# References of the articles included in the systematic review

1 Altman M, Cahill Holland J, Lundeen D, . Reduction in food away from home is associated with improved child relative weight and body composition outcomes and this relation is mediated by changes in diet quality. J Acad Nutr Diet. Sep 2015;115(9):1400–7. doi:10.1016/j.jand.2015.03.009 25963602
2 Alviso-Orellana C, Estrada-Tejada D, Carrillo-Larco RM, Bernabe-Ortiz A. Sweetened beverages, snacks and overweight: findings from the Young Lives cohort study in Peru. Public Health Nutr. Jun 2018;21(9):1627–1633. doi:10.1017/S1368980018000320 29554988
3 Amaro-Rivera K, Molina J, Perez CM, Palacios C. Longitudinal Associations between Dietary Patterns and Weight Status in Puerto Rican Infants and Toddlers’ Participants of the WIC Program. P R Health Sci J. Jun 2019;38(2):75–80.31260549
4 Ambrosini GL, Oddy WH, Huang RC, Mori TA, Beilin LJ, Jebb SA. Prospective associations between sugar-sweetened beverage intakes and cardiometabolic risk factors in adolescents. Am J Clin Nutr. Aug 2013;98(2):327–34. doi:10.3945/ajcn.112.051383 23719557
5 Arenaza L, Medrano M, Oses M, . The Effect of a Family-Based Lifestyle Education Program on Dietary Habits, Hepatic Fat and Adiposity Markers in 8-12-Year-Old Children with Overweight/Obesity. Nutrients. May 16 2020;12(5)doi:10.3390/nu12051443
6 Bennett AM, Murray K, Ambrosini GL, Oddy WH, Walsh JP, Zhu K. Prospective Associations of Sugar-Sweetened Beverage Consumption During Adolescence with Body Composition and Bone Mass at Early Adulthood. J Nutr. Feb 8 2022;152(2):399–407. doi:10.1093/jn/nxab389 34791346
7 Berkey CS, Rockett HR, Field AE, Gillman MW, Colditz GA. Sugar-added beverages and adolescent weight change. Obes Res. May 2004;12(5):778–88. doi:10.1038/oby.2004.94 15166298
8 Bigornia SJ, LaValley MP, Noel SE, Moore LL, Ness AR, Newby PK. Sugar-sweetened beverage consumption and central and total adiposity in older children: a prospective study accounting for dietary reporting errors. Public Health Nutr. May 2015;18(7):1155–63. doi:10.1017/S1368980014001700 25166959
9 Blum JW, Jacobsen DJ, Donnelly JE. Beverage consumption patterns in elementary school aged children across a two-year period. J Am Coll Nutr. Apr 2005;24(2):93–8. doi:10.1080/07315724.2005.10719449 15798075
10 Cantoral A, Tellez-Rojo MM, Ettinger AS, Hu H, Hernandez-Avila M, Peterson K. Early introduction and cumulative consumption of sugar-sweetened beverages during the pre-school period and risk of obesity at 8-14 years of age. Pediatr Obes. Feb 2016;11(1):68–74. doi:10.1111/ijpo.12023 25891908
11 Carlson JA, Crespo NC, Sallis JF, Patterson RE, Elder JP. Dietary-related and physical activity-related predictors of obesity in children: a 2-year prospective study. Child Obes. Apr 2012;8(2):110–5. doi:10.1089/chi.2011.0071 22799510
12 Chaidez V, McNiven S, Vosti SA, Kaiser LL. Sweetened food purchases and indulgent feeding are associated with increased toddler anthropometry. J Nutr Educ Behav. Jul-Aug 2014;46(4):293–298. doi:10.1016/j.jneb.2013.05.011 24188800
13 Chen JL, Guedes CM, Lung AE. Smartphone-based Healthy Weight Management Intervention for Chinese American Adolescents: Short-term Efficacy and Factors Associated With Decreased Weight. J Adolesc Health. Apr 2019;64(4):443–449. doi:10.1016/j.jadohealth.2018.08.022 30409751
14 De Coen V, De Bourdeaudhuij I, Verbestel V, Maes L, Vereecken C. Risk factors for childhood overweight: a 30-month longitudinal study of 3- to 6-year-old children. Public Health Nutr. Sep 2014;17(9):1993–2000. doi:10.1017/S1368980013002346 24172063
15 de Ruyter JC, Olthof MR, Seidell JC, Katan MB. A trial of sugar-free or sugar-sweetened beverages and body weight in children. N Engl J Med. Oct 11 2012;367(15):1397–406. doi:10.1056/NEJMoa1203034 22998340
16 DeBoer MD, Scharf RJ, Demmer RT. Sugar-sweetened beverages and weight gain in 2- to 5-year-old children. Pediatrics. Sep 2013;132(3):413–20. doi:10.1542/peds.2013-0570 23918897
17 Dong D, Bilger M, van Dam RM, Finkelstein EA. Consumption Of Specific Foods And Beverages And Excess Weight Gain Among Children And Adolescents. Health Aff (Millwood). Nov 2015;34(11):1940–8. doi:10.1377/hlthaff.2015.0434 26526253
18 Drenowatz C, Kobel S, Kettner S, . Correlates of weight gain in German children attending elementary school. Prev Med. Oct 2013;57(4):310–4. doi:10.1016/j.ypmed.2013.06.004 23769901
19 Dubois L, Farmer A, Girard M, Peterson K. Regular sugar-sweetened beverage consumption between meals increases risk of overweight among preschool-aged children. J Am Diet Assoc. Jun 2007;107(6):924–34; discussion 934-5. doi:10.1016/j.jada.2007.03.004 17524711
20 Dubuisson AC, Zech FR, Dassy MM, Jodogne NB, Beauloye VM. Determinants of weight loss in an interdisciplinary long-term care program for childhood obesity. ISRN Obes. 2012;2012:349384. doi:10.5402/2012/349384 24527260
21 Durao C, Severo M, Oliveira A, . Evaluating the effect of energy-dense foods consumption on preschool children’s body mass index: a prospective analysis from 2 to 4 years of age. Eur J Nutr. Aug 2015;54(5):835–43. doi:10.1007/s00394-014-0762-4 25185968
22 Ebbeling CB, Feldman HA, Chomitz VR, . A randomized trial of sugar-sweetened beverages and adolescent body weight. N Engl J Med. Oct 11 2012;367(15):1407–16. doi:10.1056/NEJMoa1203388 22998339
23 Ebbeling CB, Feldman HA, Osganian SK, Chomitz VR, Ellenbogen SJ, Ludwig DS. Effects of decreasing sugar-sweetened beverage consumption on body weight in adolescents: a randomized, controlled pilot study. Pediatrics. Mar 2006;117(3):673–80. doi:10.1542/peds.2005-0983 16510646
24 Enes CC, Slater B. Variation in dietary intake and physical activity pattern as predictors of change in body mass index (BMI) Z-score among Brazilian adolescents. Rev Bras Epidemiol. Jun 2013;16(2):493–501. doi:10.1590/S1415-790X2013000200023 24142019
25 English L, Carmona YR, Peterson KE, . Changes in Sugar Sweetened Beverage Intake Are Associated with Changes in Body Composition in Mexican Adolescents: Findings from the ELEMENT Cohort. Nutrients. Feb 8 2022;14(3)doi:10.3390/nu14030719
26 Faith MS, Dennison BA, Edmunds LS, Stratton HH. Fruit juice intake predicts increased adiposity gain in children from low-income families: weight status-by-environment interaction. Pediatrics. Nov 2006;118(5):2066–75. doi:10.1542/peds.2006-1117 17079580
27 Field AE, Sonneville KR, Falbe J, . Association of sports drinks with weight gain among adolescents and young adults. Obesity (Silver Spring). Oct 2014;22(10):2238–43. doi:10.1002/oby.20845 25044989
28 Fiorito LM, Marini M, Francis LA, Smiciklas-Wright H, Birch LL. Beverage intake of girls at age 5 y predicts adiposity and weight status in childhood and adolescence. Am J Clin Nutr. Oct 2009;90(4):935–42. doi:10.3945/ajcn.2009.27623 19692492
29 French SA, Mitchell NR, Hannan PJ. Decrease in television viewing predicts lower body mass index at 1-year follow-up in adolescents, but not adults. J Nutr Educ Behav. Sep-Oct 2012;44(5):415–22. doi:10.1016/j.jneb.2011.12.008 22591582
30 Garden FL, Marks GB, Almqvist C, Simpson JM, Webb KL. Infant and early childhood dietary predictors of overweight at age 8 years in the CAPS population. Eur J Clin Nutr. Apr 2011;65(4):454–62. doi:10.1038/ejcn.2011.7 21346718
31 Garden FL, Marks GB, Simpson JM, Webb KL. Body mass index (BMI) trajectories from birth to 11.5 years: relation to early life food intake. Nutrients. Oct 9 2012;4(10):1382–98. doi:10.3390/nu4101382 23201761
32 Goff LM, Huang P, Silva MJ, . Associations of dietary intake with cardiometabolic risk in a multi-ethnic cohort: a longitudinal analysis of the Determinants of Adolescence, now young Adults, Social well-being and Health (DASH) study. Br J Nutr. May 2019;121(9):1069–1079. doi:10.1017/S0007114519000291 30764887
33 Goh EK, Kim OY, Yoon SR, Jeon HJ. Timing of Adiposity Rebound and Determinants of Early Adiposity Rebound in Korean Infants and Children Based on Data from the National Health Insurance Service. Nutrients. Feb 22 2022;14(5)doi:10.3390/nu14050929
34 Gopinath B, Flood VM, Rochtchina E, . Carbohydrate nutrition and development of adiposity during adolescence. Obesity (Silver Spring). Sep 2013;21(9):1884–90. doi:10.1002/oby.20405 23519919
35 Guerrero AD, Mao C, Fuller B, Bridges M, Franke T, Kuo AA. Racial and Ethnic Disparities in Early Childhood Obesity: Growth Trajectories in Body Mass Index. J Racial Ethn Health Disparities. Mar 2016;3(1):129–37. doi:10.1007/s40615-015-0122-y 26896112
36 Haines J, Neumark-Sztainer D, Wall M, Story M. Personal, behavioral, and environmental risk and protective factors for adolescent overweight. Obesity (Silver Spring). Nov 2007;15(11):2748–60. doi:10.1038/oby.2007.327 18070766
37 Hasnain SR, Singer MR, Bradlee ML, Moore LL. Beverage intake in early childhood and change in body fat from preschool to adolescence. Child Obes. Feb 2014;10(1):42–9. doi:10.1089/chi.2013.0004 24450382
38 He Y, Luo B, Zhao L, Liao S. Influences of the COVID-19 Pandemic on Obesity and Weight-Related Behaviors among Chinese Children: A Multi-Center Longitudinal Study. Nutrients. Sep 10 2022;14(18)doi:10.3390/nu14183744
39 Hooley M, Skouteris H, Millar L. The relationship between childhood weight, dental caries and eating practices in children aged 4-8 years in Australia, 2004-2008. Pediatr Obes. Dec 2012;7(6):461–70. doi:10.1111/j.2047-6310.2012.00072.x 22911896
40 Hur YI, Park H, Kang JH, . Associations between Sugar Intake from Different Food Sources and Adiposity or Cardio-Metabolic Risk in Childhood and Adolescence: The Korean Child-Adolescent Cohort Study. Nutrients. Dec 31 2015;8(1)doi:10.3390/nu8010020
41 Hwang IT, Ju YS, Lee HJ, Shim YS, Jeong HR, Kang MJ. Body mass index trajectories and adiposity rebound during the first 6 years in Korean children: Based on the National Health Information Database, 2008-2015. PLoS One. 2020;15(10):e0232810. doi:10.1371/journal.pone.0232810 33125366
42 Jensen BW, Nichols M, Allender S, . Inconsistent associations between sweet drink intake and 2-year change in BMI among Victorian children and adolescents. Pediatr Obes. Aug 2013;8(4):271–83. doi:10.1111/j.2047-6310.2013.00174.x 23785025
43 Jensen BW, Nielsen BM, Husby I, . Association between sweet drink intake and adiposity in Danish children participating in a long-term intervention study. Pediatr Obes. Aug 2013;8(4):259–70. doi:10.1111/j.2047-6310.2013.00170.x 23630030
44 Johnson BA, Kremer PJ, Swinburn BA, de Silva-Sanigorski AM. Multilevel analysis of the Be Active Eat Well intervention: environmental and behavioural influences on reductions in child obesity risk. Int J Obes (Lond). Jul 2012;36(7):901–7. doi:10.1038/ijo.2012.23 22531087
45 Johnson L, Mander AP, Jones LR, Emmett PM, Jebb SA. Is sugar-sweetened beverage consumption associated with increased fatness in children? Nutrition. Jul-Aug 2007;23(7-8):557–63. doi:10.1016/j.nut.2007.05.005 17616342
46 Katan MB, de Ruyter JC, Kuijper LD, Chow CC, Hall KD, Olthof MR. Impact of Masked Replacement of Sugar-Sweetened with Sugar-Free Beverages on Body Weight Increases with Initial BMI: Secondary Analysis of Data from an 18 Month Double-Blind Trial in Children. PLoS One. 2016;11(7):e0159771. doi:10.1371/journal.pone.0159771 27447721
47 Kral TV, Stunkard AJ, Berkowitz RI, Stallings VA, Moore RH, Faith MS. Beverage consumption patterns of children born at different risk of obesity. Obesity (Silver Spring). Aug 2008;16(8):1802–8. doi:10.1038/oby.2008.287 18535546
48 Kuhl ES, Clifford LM, Bandstra NF, . Examination of the association between lifestyle behavior changes and weight outcomes in preschoolers receiving treatment for obesity. Health Psychol. Jan 2014;33(1):95–8. doi:10.1037/a0032741 23815763
49 Kunaratnam K, Halaki M, Wen LM, Baur LA, Flood VM. Tracking Preschoolers’ Lifestyle Behaviors and Testing Maternal Sociodemographics and BMI in Predicting Child Obesity Risk. J Nutr. Dec 10 2020;150(12):3068–3074. doi:10.1093/jn/nxaa292 33096560
50 Larson N, Chen Y, Wall M, Winkler MR, Goldschmidt AB, Neumark-Sztainer D. Personal, behavioral, and environmental predictors of healthy weight maintenance during the transition to adulthood. Prev Med. Aug 2018;113:80–90. doi:10.1016/j.ypmed.2018.04.027 29727637
51 Laska MN, Murray DM, Lytle LA, Harnack LJ. Longitudinal associations between key dietary behaviors and weight gain over time: transitions through the adolescent years. Obesity (Silver Spring). Jan 2012;20(1):118–25. doi:10.1038/oby.2011.179 21701567
52 Laurson K, Eisenmann JC, Moore S. Lack of association between television viewing, soft drinks, physical activity and body mass index in children. Acta Paediatr. Jun 2008;97(6):795–800. doi:10.1111/j.1651-2227.2008.00713.x 18410467
53 Lee AK, Chowdhury R, Welsh JA. Sugars and adiposity: the long-term effects of consuming added and naturally occurring sugars in foods and in beverages. Obes Sci Pract. Oct 2015;1(1):41–49. doi:10.1002/osp4.7 27774248
54 Leermakers ET, Felix JF, Erler NS, . Sugar-containing beverage intake in toddlers and body composition up to age 6 years: the Generation R study. Eur J Clin Nutr. Mar 2015;69(3):314–21. doi:10.1038/ejcn.2015.2 25649238
55 Leermakers ET, Felix JF, Jaddoe VW, Raat H, Franco OH, Kiefte-de Jong JC. Sugar-containing beverage intake at the age of 1 year and cardiometabolic health at the age of 6 years: the Generation R Study. Int J Behav Nutr Phys Act. Sep 17 2015;12:114. doi:10.1186/s12966-015-0278-1 26377916
56 Lewis KH, Skelton J, Hsu FC, Ezouah P, Taveras EM, Block JP. Use of Electronic Health Record Data to Study the Association of Sugary Drink Consumption With Child Weight Status. Acad Pediatr. Aug 2020;20(6):767–775. doi:10.1016/j.acap.2019.11.002 31712182
57 Li R, Fein SB, Grummer-Strawn LM. Association of breastfeeding intensity and bottle-emptying behaviors at early infancy with infants’ risk for excess weight at late infancy. Pediatrics. Oct 2008;122 Suppl 2:S77–84. doi:10.1542/peds.2008-1315j 18829835
58 Libuda L, Alexy U, Sichert-Hellert W, . Pattern of beverage consumption and long-term association with body-weight status in German adolescents-results from the DONALD study. Br J Nutr. Jun 2008;99(6):1370–9. doi:10.1017/S0007114507862362 18034911
59 Lim S, Zoellner JM, Lee JM, . Obesity and sugar-sweetened beverages in African-American preschool children: a longitudinal study. Obesity (Silver Spring). Jun 2009;17(6):1262–8. doi:10.1038/oby.2008.656 19197261
60 Lipsky LM, Haynie DL, Liu D, . Trajectories of eating behaviors in a nationally representative cohort of U.S. adolescents during the transition to young adulthood. Int J Behav Nutr Phys Act. Nov 4 2015;12:138. doi:10.1186/s12966-015-0298-x 26537771
61 Ludwig DS, Peterson KE, Gortmaker SL. Relation between consumption of sugar-sweetened drinks and childhood obesity: a prospective, observational analysis. Lancet. Feb 17 2001;357(9255):505–8. doi:10.1016/S0140-6736(00)04041-1 11229668
62 Macintyre AK, Marryat L, Chambers S. Exposure to liquid sweetness in early childhood: artificially-sweetened and sugar-sweetened beverage consumption at 4-5 years and risk of overweight and obesity at 7-8 years. Pediatr Obes. Dec 2018;13(12):755–765. doi:10.1111/ijpo.12284 29624909
63 Mahoney S, Bryant M, Sahota P, Barber S. Dietary intake in the early years and its relationship to BMI in a bi-ethnic group: the Born in Bradford 1000 study. Public Health Nutr. Aug 2018;21(12):2242–2254. doi:10.1017/S1368980018000654 29607793
64 Malihi Z, Portch R, Hashemi L, . Modifiable Early Childhood Risk Factors for Obesity at Age Four Years. Child Obes. Apr 2021;17(3):196–208. doi:10.1089/chi.2020.0174 33595354
65 Marshall TA, Curtis AM, Cavanaugh JE, Warren JJ, Levy SM. Higher Longitudinal Milk Intakes Are Associated with Increased Height in a Birth Cohort Followed for 17 Years. J Nutr. Jul 1 2018;148(7):1144–1149. doi:10.1093/jn/nxy071 29924327
66 Marshall TA, Curtis AM, Cavanaugh JE, Warren JJ, Levy SM. Child and Adolescent Sugar-Sweetened Beverage Intakes Are Longitudinally Associated with Higher Body Mass Index z Scores in a Birth Cohort Followed 17 Years. J Acad Nutr Diet. Mar 2019;119(3):425–434. doi:10.1016/j.jand.2018.11.003 30638821
67 Millar L, Rowland B, Nichols M, . Relationship between raised BMI and sugar sweetened beverage and high fat food consumption among children. Obesity (Silver Spring). May 2014;22(5):E96–103. doi:10.1002/oby.20665 24318968
68 Mirmiran P, Yuzbashian E, Asghari G, Hosseinpour-Niazi S, Azizi F. Consumption of sugar sweetened beverage is associated with incidence of metabolic syndrome in Tehranian children and adolescents. Nutr Metab (Lond). 2015;12:25. doi:10.1186/s12986-015-0021-6 26225136
69 Mrdjenovic G, Levitsky DA. Nutritional and energetic consequences of sweetened drink consumption in 6- to 13-year-old children. J Pediatr. Jun 2003;142(6):604–10. doi:10.1067/mpd.2003.200 12838186
70 Muckelbauer R, Gortmaker SL, Libuda L, . Changes in water and sugar-containing beverage consumption and body weight outcomes in children. Br J Nutr. Jun 2016;115(11):2057–66. doi:10.1017/S0007114516001136 27040694
71 Mundt CA, Baxter-Jones AD, Whiting SJ, Bailey DA, Faulkner RA, Mirwald RL. Relationships of activity and sugar drink intake on fat mass development in youths. Med Sci Sports Exerc. Jul 2006;38(7):1245–54. doi:10.1249/01.mss.0000227309.18902.fe 16826021
72 Newby PK, Peterson KE, Berkey CS, Leppert J, Willett WC, Colditz GA. Beverage consumption is not associated with changes in weight and body mass index among low-income preschool children in North Dakota. J Am Diet Assoc. Jul 2004;104(7):1086–94. doi:10.1016/j.jada.2004.04.020 15215766
73 Nissinen K, Mikkila V, Mannisto S, . Sweets and sugar-sweetened soft drink intake in childhood in relation to adult BMI and overweight. The Cardiovascular Risk in Young Finns Study. Public Health Nutr. Nov 2009;12(11):2018–26. doi:10.1017/S1368980009005849 19476678
74 Olsen NJ, Andersen LB, Wedderkopp N, Kristensen PL, Heitmann BL. Intake of liquid and solid sucrose in relation to changes in body fatness over 6 years among 8- to 10-year-old children: the European Youth Heart Study. Obes Facts. 2012;5(4):506–12. doi:10.1159/000341631 22854439
75 Pan L, Li R, Park S, Galuska DA, Sherry B, Freedman DS. A longitudinal analysis of sugar-sweetened beverage intake in infancy and obesity at 6 years. Pediatrics. Sep 2014;134 Suppl 1(Suppl 1):S29…35. doi:10.1542/peds.2014-0646F 25183752
76 Pereyra-Gonzalez I, Mattei J. Combined intake of sugar-sweetened beverages and sugar-containing ultra-processed foods is associated with an increase in body mass index during early childhood. Pediatr Obes. Jun 2023;18(6):e13025. doi:10.1111/ijpo.13025 36945180
77 Phillips SM, Bandini LG, Naumova EN, . Energy-dense snack food intake in adolescence: longitudinal relationship to weight and fatness. Obes Res. Mar 2004;12(3):461–72. doi:10.1038/oby.2004.52 15044663
78 Quah PL, Kleijweg J, Chang YY, . Association of sugar-sweetened beverage intake at 18 months and 5 years of age with adiposity outcomes at 6 years of age: the Singapore GUSTO mother-offspring cohort. Br J Nutr. Dec 14 2019;122(11):1303–1312. doi:10.1017/S0007114519002253 31477198
79 Quick V, Wall M, Larson N, Haines J, Neumark-Sztainer D. Personal, behavioral and socioenvironmental predictors of overweight incidence in young adults: 10-yr longitudinal findings. Int J Behav Nutr Phys Act. Mar 25 2013;10:37. doi:10.1186/1479-5868-10-37 23531253
80 Seo DC, King MH, Kim N, Sovinski D, Meade R, Lederer AM. Predictors for Persistent Overweight, Deteriorated Weight Status, and Improved Weight Status During 18 Months in a School-Based Longitudinal Cohort. Am J Health Promot. Sep-Oct 2015;30(1):22–7. doi:10.4278/ajhp.131118-QUAN-585 25372231
81 Seum T, Meyrose AK, Rabel M, Schienkiewitz A, Ravens-Sieberer U. Pathways of Parental Education on Children’s and Adolescent’s Body Mass Index: The Mediating Roles of Behavioral and Psychological Factors. Front Public Health. 2022;10:763789. doi:10.3389/fpubh.2022.763789 35321198
82 Shroff MR, Perng W, Baylin A, Mora-Plazas M, Marin C, Villamor E. Adherence to a snacking dietary pattern and soda intake are related to the development of adiposity: a prospective study in school-age children. Public Health Nutr. Jul 2014;17(7):1507–13. doi:10.1017/S136898001300133X 23701749
83 Sichieri R, Yokoo EM, Pereira RA, Veiga GV. Water and sugar-sweetened beverage consumption and changes in BMI among Brazilian fourth graders after 1-year follow-up. Public Health Nutr. Jan 2013;16(1):73–7. doi:10.1017/S1368980012001309 22640686
84 Sonneville KR, Long MW, Rifas-Shiman SL, Kleinman K, Gillman MW, Taveras EM. Juice and water intake in infancy and later beverage intake and adiposity: could juice be a gateway drink? Obesity (Silver Spring). Jan 2015;23(1):170–6. doi:10.1002/oby.20927 25328160
85 Stoof SP, Twisk JW, Olthof MR. Is the intake of sugar-containing beverages during adolescence related to adult weight status? Public Health Nutr. Jul 2013;16(7):1257–62. doi:10.1017/S1368980011002783 22067526
86 Striegel-Moore RH, Thompson D, Affenito SG, . Correlates of beverage intake in adolescent girls: the National Heart, Lung, and Blood Institute Growth and Health Study. J Pediatr. Feb 2006;148(2):183–7. doi:10.1016/j.jpeds.2005.11.025 16492426
87 Tam CS, Garnett SP, Cowell CT, Campbell K, Cabrera G, Baur LA. Soft drink consumption and excess weight gain in Australian school students: results from the Nepean study. Int J Obes (Lond). Jul 2006;30(7):1091–3. doi:10.1038/sj.ijo.0803328 16801946
88 Thurber KA, Dobbins T, Neeman T, Banwell C, Banks E. Body mass index trajectories of Indigenous Australian children and relation to screen time, diet, and demographic factors. Obesity (Silver Spring). Apr 2017;25(4):747–756. doi:10.1002/oby.21783 28349661
89 Traub M, Lauer R, Kesztyus T, . Skipping breakfast, overconsumption of soft drinks and screen media: longitudinal analysis of the combined influence on weight development in primary schoolchildren. BMC Public Health. Mar 16 2018;18(1):363. doi:10.1186/s12889-018-5262-7 29548323
90 Trier C, Fonvig CE, Bojsoe C, . No influence of sugar, snacks and fast food intake on the degree of obesity or treatment effect in childhood obesity. Pediatr Obes. Dec 2016;11(6):506–512. doi:10.1111/ijpo.12094 26909660
91 Vandyousefi S, Davis JN, Gunderson EP. Association of infant diet with subsequent obesity at 2-5 years among children exposed to gestational diabetes: the SWIFT study. Diabetologia. May 2021;64(5):1121–1132. doi:10.1007/s00125-020-05379-y 33495846
92 Vanselow MS, Pereira MA, Neumark-Sztainer D, Raatz SK. Adolescent beverage habits and changes in weight over time: findings from Project EAT. Am J Clin Nutr. Dec 2009;90(6):1489–95. doi:10.3945/ajcn.2009.27573 19864412
93 Viner RM, Cole TJ. Who changes body mass between adolescence and adulthood? Factors predicting change in BMI between 16 year and 30 years in the 1970 British Birth Cohort. Int J Obes (Lond). Sep 2006;30(9):1368–74. doi:10.1038/sj.ijo.0803183 16552412
94 Vinke PC, Blijleven KA, Luitjens M, Corpeleijn E. Young Children’s Sugar-Sweetened Beverage Consumption and 5-Year Change in BMI: Lessons Learned from the Timing of Consumption. Nutrients. Aug 18 2020;12(8)doi:10.3390/nu12082486
95 Wang C, Chen Y, Hong X, . Reduced Consumption of Sugar-Sweetened Beverages Is Associated with Lower Body Mass Index Z-Score Gain among Chinese Schoolchildren. Nutrients. Oct 1 2022;14(19)doi:10.3390/nu14194088
96 Welsh JA, Cogswell ME, Rogers S, Rockett H, Mei Z, Grummer-Strawn LM. Overweight among low-income preschool children associated with the consumption of sweet drinks: Missouri, 1999-2002. Pediatrics. Feb 2005;115(2):e223–9. doi:10.1542/peds.2004-1148 15687430
97 Wheaton N, Millar L, Allender S, Nichols M. The stability of weight status through the early to middle childhood years in Australia: a longitudinal study. BMJ Open. Apr 28 2015;5(4):e006963. doi:10.1136/bmjopen-2014-006963
98 Whetstone LM, Kolasa KM, Collier DN. Participation in community-originated interventions is associated with positive changes in weight status and health behaviors in youth. Am J Health Promot. Sep-Oct 2012;27(1):10–6. doi:10.4278/ajhp.100415-QUAN-117 22950920
99 Wijga AH, Scholtens S, Bemelmans WJ, . Diet, Screen Time, Physical Activity, and Childhood Overweight in the General Population and in High Risk Subgroups: Prospective Analyses in the PIAMA Birth Cohort. J Obes. 2010;2010doi:10.1155/2010/423296
100 Wu AJ, Aris IM, Hivert MF, . Associations of Healthy Infant Feeding Practices and Early Childhood Adiposity in the Rise & SHINE Cohort. J Pediatr Gastroenterol Nutr. Aug 1 2022;75(2):e15–e19. doi:10.1097/MPG.0000000000003495 35641893
101 Wu AJ, Aris IM, Rifas-Shiman SL, Oken E, Taveras EM, Hivert MF. Longitudinal associations of fruit juice intake in infancy with DXA-measured abdominal adiposity in mid-childhood and early adolescence. Am J Clin Nutr. Jul 1 2021;114(1):117–123. doi:10.1093/ajcn/nqab043 33829237
102 Yiotaldiotariotam M, Singh AS, te Velde SJ, . Mediators of longitudinal changes in measures of adiposity in teenagers using parallel process latent growth modeling. Obesity (Silver Spring). Nov 2013;21(11):2387–95. doi:10.1002/oby.20463 23794531
103 Yoon L, Corvalan C, Pereira A, Shepherd J, Michels KB. Sugar-sweetened beverage consumption and breast composition in a longitudinal study of Chilean girls. Breast Cancer Res. Jan 8 2022;24(1):3. doi:10.1186/s13058-021-01495-8 34998441
104 Zhang T, Au Yeung SL, Kwok MK, Hui LL, Leung GM, Schooling CM. Association of Sugar-Sweetened Beverage Frequency with Adiposity: Evidence from the “Children of 1997” Birth Cohort. Nutrients. Apr 7 2020;12(4)doi:10.3390/nu12041015
105 Zheng M, Allman-Farinelli M, Heitmann BL, . Liquid versus solid energy intake in relation to body composition among Australian children. J Hum Nutr Diet. Feb 2015;28 Suppl 2:70–9. doi:10.1111/jhn.12223 24548259
106 Zheng M, Rangan A, Allman-Farinelli M, Rohde JF, Olsen NJ, Heitmann BL. Replacing sugary drinks with milk is inversely associated with weight gain among young obesity-predisposed children. Br J Nutr. Nov 14 2015;114(9):1448–55. doi:10.1017/S0007114515002974 26328600
107 Zheng M, Rangan A, Huang RC, . Modelling the Effects of Beverage Substitution during Adolescence on Later Obesity Outcomes in Early Adulthood: Results from the Raine Study. Nutrients. Dec 3 2019;11(12)doi:10.3390/nu11122928
108 Zheng M, Rangan A, Olsen NJ, . Substituting sugar-sweetened beverages with water or milk is inversely associated with body fatness development from childhood to adolescence. Nutrition. Jan 2015;31(1):38–44. doi:10.1016/j.nut.2014.04.017 25441586
109 Zheng M, Rangan A, Olsen NJ, . Sugar-sweetened beverages consumption in relation to changes in body fatness over 6 and 12 years among 9-year-old children: the European Youth Heart Study. Eur J Clin Nutr. Jan 2014;68(1):77–83. doi:10.1038/ejcn.2013.243 24281311
110 Zulfiqar T, Strazdins L, Dinh H, Banwell C, D’Este C. Drivers of Overweight/Obesity in 4-11 Year Old Children of Australians and Immigrants; Evidence from Growing Up in Australia. J Immigr Minor Health. Aug 2019;21(4):737–750. doi:10.1007/s10903-018-0841-3 30484000
111 Dubois L, Diasparra M, Bogl LH, . Dietary Intake at 9 Years and Subsequent Body Mass Index in Adolescent Boys and Girls: A Study of Monozygotic Twin Pairs. Twin Res Hum Genet. Feb 2016;19(1):47–59. doi:10.1017/thg.2015.97 26810866
112 Acero D, Zoellner JM, Davy BM, Hedrick VE. Changes in Non-Nutritive Sweetener Consumption Patterns in Response to a Sugar-Sweetened Beverage Reduction Intervention. Nutrients. Nov 8 2020;12(11)doi:10.3390/nu12113428
113 Appelhans BM, Baylin A, Huang MH, . Beverage Intake and Metabolic Syndrome Risk Over 14 Years: The Study of Women’s Health Across the Nation. J Acad Nutr Diet. Apr 2017;117(4):554–562. doi:10.1016/j.jand.2016.10.011 27938940
114 Auerbach BJ, Littman AJ, Krieger J, . Association of 100% fruit juice consumption and 3-year weight change among postmenopausal women in the in the Women’s Health Initiative. Prev Med. Apr 2018;109:8–10. doi:10.1016/j.ypmed.2018.01.004 29330029
115 Barone Gibbs B, Kinzel LS, Pettee Gabriel K, Chang YF, Kuller LH. Short- and long-term eating habit modification predicts weight change in overweight, postmenopausal women: results from the WOMAN study. J Acad Nutr Diet. Sep 2012;112(9):1347–1355 e2. doi:10.1016/j.jand.2012.06.012 22939439
116 Barrio-Lopez MT, Martinez-Gonzalez MA, Fernandez-Montero A, Beunza JJ, Zazpe I, Bes-Rastrollo M. Prospective study of changes in sugar-sweetened beverage consumption and the incidence of the metabolic syndrome and its components: the SUN cohort. Br J Nutr. Nov 14 2013;110(9):1722–31. doi:10.1017/S0007114513000822 23534417
117 Bes-Rastrollo M, Sanchez-Villegas A, Gomez-Gracia E, Martinez JA, Pajares RM, Martinez-Gonzalez MA. Predictors of weight gain in a Mediterranean cohort: the Seguimiento Universidad de Navarra Study 1. Am J Clin Nutr. Feb 2006;83(2):362–70; quiz 394-5. doi:10.1093/ajcn/83.2.362 16469996
118 Bes-Rastrollo M, van Dam RM, Martinez-Gonzalez MA, Li TY, Sampson LL, Hu FB. Prospective study of dietary energy density and weight gain in women. Am J Clin Nutr. Sep 2008;88(3):769–77. doi:10.1093/ajcn/88.3.769 18779295
119 Boggs DA, Rosenberg L, Coogan PF, Makambi KH, Adams-Campbell LL, Palmer JR. Restaurant foods, sugar-sweetened soft drinks, and obesity risk among young African American women. Ethn Dis. Autumn 2013;23(4):445–51.24392607
120 Bundrick SC, Thearle MS, Venti CA, Krakoff J, Votruba SB. Soda consumption during ad libitum food intake predicts weight change. J Acad Nutr Diet. Mar 2014;114(3):444–449. doi:10.1016/j.jand.2013.09.016 24321742
121 Buso MEC, Brouwer-Brolsma EM, Naomi ND, . Dose-Response and Substitution Analyzes of Sweet Beverage Consumption and Body Weight in Dutch Adults: The Lifelines Cohort Study. Front Nutr. 2022;9:889042. doi:10.3389/fnut.2022.889042 35832052
122 Campos V, Despland C, Brandejsky V, . Sugar- and artificially sweetened beverages and intrahepatic fat: A randomized controlled trial. Obesity (Silver Spring). Dec 2015;23(12):2335–9. doi:10.1002/oby.21310 26727115
123 Carroll SJ, Niyonsenga T, Coffee NT, Taylor AW, Daniel M. Associations between local descriptive norms for overweight/obesity and insufficient fruit intake, individual-level diet, and 10-year change in body mass index and glycosylated haemoglobin in an Australian cohort. Int J Behav Nutr Phys Act. May 18 2018;15(1):44. doi:10.1186/s12966-018-0675-3 29776358
124 Castellana F, Zupo R, Bortone I, . Traditional Old Dietary Pattern of Castellana Grotte (Apulia) Is Associated with Healthy Outcomes. Nutrients. Oct 12 2020;12(10)doi:10.3390/nu12103097
125 Chen L, Appel LJ, Loria C, . Reduction in consumption of sugar-sweetened beverages is associated with weight loss: the PREMIER trial. Am J Clin Nutr. May 2009;89(5):1299–306. doi:10.3945/ajcn.2008.27240 19339405
126 Chen L, Caballero B, Mitchell DC, . Reducing consumption of sugar-sweetened beverages is associated with reduced blood pressure: a prospective study among United States adults. Circulation. Jun 8 2010;121(22):2398–406. doi:10.1161/CIRCULATIONAHA.109.911164 20497980
127 Cleland VJ, Patterson K, Breslin M, Schmidt MD, Dwyer T, Venn AJ. Longitudinal associations between TV viewing and BMI not explained by the ‘mindless eating’ or ‘physical activity displacement’ hypotheses among adults. BMC Public Health. Jun 26 2018;18(1):797. doi:10.1186/s12889-018-5674-4 29940922
128 Dhingra R, Sullivan L, Jacques PF, . Soft drink consumption and risk of developing cardiometabolic risk factors and the metabolic syndrome in middle-aged adults in the community. Circulation. Jul 31 2007;116(5):480–8. doi:10.1161/CIRCULATIONAHA.107.689935 17646581
129 Drapeau V, Després JP, Bouchard C, . Modifications in food-group consumption are related to long-term body-weight changes. Am J Clin Nutr. Jul 2004;80(1):29–37. doi:10.1093/ajcn/80.1.29 15213024
130 Duffey KJ, Gordon-Larsen P, Steffen LM, Jacobs DR, Jr., Popkin BM. Drinking caloric beverages increases the risk of adverse cardiometabolic outcomes in the Coronary Artery Risk Development in Young Adults (CARDIA) Study. Am J Clin Nutr. Oct 2010;92(4):954–9. doi:10.3945/ajcn.2010.29478 20702604
131 Ebbeling CB, Feldman HA, Steltz SK, Quinn NL, Robinson LM, Ludwig DS. Effects of Sugar-Sweetened, Artificially Sweetened, and Unsweetened Beverages on Cardiometabolic Risk Factors, Body Composition, and Sweet Taste Preference: A Randomized Controlled Trial. J Am Heart Assoc. Aug 4 2020;9(15):e015668. doi:10.1161/JAHA.119.015668 32696704
132 Ferreira-Pego C, Babio N, Bes-Rastrollo M, . Frequent Consumption of Sugar- and Artificially Sweetened Beverages and Natural and Bottled Fruit Juices Is Associated with an Increased Risk of Metabolic Syndrome in a Mediterranean Population at High Cardiovascular Disease Risk. J Nutr. Aug 2016;146(8):1528–36. doi:10.3945/jn.116.230367 27358413
133 Fowler SP, Williams K, Hazuda HP. Diet soda intake is associated with long-term increases in waist circumference in a biethnic cohort of older adults: the San Antonio Longitudinal Study of Aging. J Am Geriatr Soc. Apr 2015;63(4):708–15. doi:10.1111/jgs.13376 25780952
134 Fowler SP, Williams K, Resendez RG, Hunt KJ, Hazuda HP, Stern MP. Fueling the obesity epidemic? Artificially sweetened beverage use and long-term weight gain. Obesity (Silver Spring). Aug 2008;16(8):1894–900. doi:10.1038/oby.2008.284 18535548
135 Funtikova AN, Subirana I, Gomez SF, . Soft drink consumption is positively associated with increased waist circumference and 10-year incidence of abdominal obesity in Spanish adults. J Nutr. Feb 2015;145(2):328–34. doi:10.3945/jn.114.205229 25644355
136 Garduno-Alanis A, Malyutina S, Pajak A, . Association between soft drink, fruit juice consumption and obesity in Eastern Europe: cross-sectional and longitudinal analysis of the HAPIEE study. J Hum Nutr Diet. Feb 2020;33(1):66–77. doi:10.1111/jhn.12696 31475413
137 Gearon E, Peeters A, Ng W, Hodge A, Backholer K. Diet and physical activity as possible mediators of the association between educational attainment and body mass index gain among Australian adults. Int J Public Health. Sep 2018;63(7):883–893. doi:10.1007/s00038-018-1100-z 29687156
138 Gibbs BB, Tudorascu D, Bryce CL, . Lifestyle Habits Associated with Weight Regain After Intentional Loss in Primary Care Patients Participating in a Randomized Trial. J Gen Intern Med. Nov 2020;35(11):3227–3233. doi:10.1007/s11606-020-06056-x 32808209
139 Gonzalez-Morales R, Canto-Osorio F, Stern D, . Soft drink intake is associated with weight gain, regardless of physical activity levels: the health workers cohort study. Int J Behav Nutr Phys Act. May 12 2020;17(1):60. doi:10.1186/s12966-020-00963-2 32398158
140 Halkjaer J, Tjonneland A, Overvad K, Sorensen TI. Dietary predictors of 5-year changes in waist circumference. J Am Diet Assoc. Aug 2009;109(8):1356–66. doi:10.1016/j.jada.2009.05.015 19631041
141 Hasselbalch AL, Heitmann BL, Kyvik KO, Sorensen TI. Associations between dietary intake and body fat independent of genetic and familial environmental background. Int J Obes (Lond). May 2010;34(5):892–8. doi:10.1038/ijo.2010.1 20125102
142 Hernandez-Cordero S, Barquera S, Rodriguez-Ramirez S, . Substituting water for sugar-sweetened beverages reduces circulating triglycerides and the prevalence of metabolic syndrome in obese but not in overweight Mexican women in a randomized controlled trial. J Nutr. Nov 2014;144(11):1742–52. doi:10.3945/jn.114.193490 25332472
143 Higgins KA, Mattes RD. A randomized controlled trial contrasting the effects of 4 low-calorie sweeteners and sucrose on body weight in adults with overweight or obesity. Am J Clin Nutr. May 1 2019;109(5):1288–1301. doi:10.1093/ajcn/nqy381 30997499
144 Hosseinpour-Niazi S, Aghayan M, Mirmiran P, Azizi F. Does weight change modify the association between the consumption of sugar-sweetened beverages and 100% fruit juice and the risk of metabolic syndrome? Clin Nutr. Oct 2021;40(10):5261–5268. doi:10.1016/j.clnu.2021.08.017 34534895
145 Inoue M, Toyokawa S, Inoue K, . Lifestyle, weight perception and change in body mass index of Japanese workers: MY Health Up Study. Public Health. Sep 2010;124(9):530–7. doi:10.1016/j.puhe.2010.04.009 20728909
146 Kaikkonen JE, Mikkila V, Juonala M, . Factors associated with six-year weight change in young and middle-aged adults in the Young Finns Study. Scand J Clin Lab Invest. Apr 2015;75(2):133–44. doi:10.3109/00365513.2014.992945 25600675
147 Kang Y, Kim J. Soft drink consumption is associated with increased incidence of the metabolic syndrome only in women. Br J Nutr. Jan 2017;117(2):315–324. doi:10.1017/S0007114517000046 28166856
148 Karkkainen U, Mustelin L, Raevuori A, Kaprio J, Keski-Rahkonen A. Successful weight maintainers among young adults-A ten-year prospective population study. Eat Behav. Apr 2018;29:91–98. doi:10.1016/j.eatbeh.2018.03.004 29549864
149 Kendig MD, Chow JYL, Martire SI, Rooney KB, Boakes RA. Switching from Sugar- to Artificially-Sweetened Beverages: A 12-Week Trial. Nutrients. May 4 2023;15(9)doi:10.3390/nu15092191
150 Konieczna J, Romaguera D, Pereira V, . Longitudinal association of changes in diet with changes in body weight and waist circumference in subjects at high cardiovascular risk: the PREDIMED trial. Int J Behav Nutr Phys Act. Dec 27 2019;16(1):139. doi:10.1186/s12966-019-0893-3 31882021
151 Kvaavik E, Andersen LF, Klepp KI. The stability of soft drinks intake from adolescence to adult age and the association between long-term consumption of soft drinks and lifestyle factors and body weight. Public Health Nutr. Apr 2005;8(2):149–57. doi:10.1079/phn2004669 15877908
152 Lim CGY, Whitton C, Rebello SA, van Dam RM. Diet Quality and Lower Refined Grain Consumption are Associated With Less Weight Gain in a Multi-Ethnic Asian Adult Population. J Nutr. Aug 7 2021;151(8):2372–2382. doi:10.1093/jn/nxab110 33978192
153 Ma J, McKeown NM, Hwang SJ, Hoffmann U, Jacques PF, Fox CS. Sugar-Sweetened Beverage Consumption Is Associated With Change of Visceral Adipose Tissue Over 6 Years of Follow-Up. Circulation. Jan 26 2016;133(4):370–7. doi:10.1161/CIRCULATIONAHA.115.018704 26755505
154 Maersk M, Belza A, Stodkilde-Jorgensen H, . Sucrose-sweetened beverages increase fat storage in the liver, muscle, and visceral fat depot: a 6-mo randomized intervention study. Am J Clin Nutr. Feb 2012;95(2):283–9. doi:10.3945/ajcn.111.022533 22205311
155 Moshtaghian H, Charlton KE, Louie JCY, Probst YC, Mitchell P, Flood VM. Changes in Added Sugar Intake and Body Weight in a Cohort of Older Australians: A Secondary Analysis of the Blue Mountains Eye Study. Front Nutr. 2021;8:629815. doi:10.3389/fnut.2021.629815 33732727
156 Mozaffarian D, Hao T, Rimm EB, Willett WC, Hu FB. Changes in diet and lifestyle and long-term weight gain in women and men. N Engl J Med. Jun 23 2011;364(25):2392–404. doi:10.1056/NEJMoa1014296 21696306
157 Mullie P, Autier P, Boniol M, . Assessment of sugar-sweetened beverage consumption and weight change: a prospective cohort study. BMC Nutr. 2017;3:57. doi:10.1186/s40795-017-0182-y 32153837
158 Nooyens AC, Visscher TL, Schuit AJ, . Effects of retirement on lifestyle in relation to changes in weight and waist circumference in Dutch men: a prospective study. Public Health Nutr. Dec 2005;8(8):1266–74. doi:10.1079/phn2005756 16372922
159 Odegaard AO, Koh WP, Arakawa K, Yu MC, Pereira MA. Soft drink and juice consumption and risk of physician-diagnosed incident type 2 diabetes: the Singapore Chinese Health Study. Am J Epidemiol. Mar 15 2010;171(6):701–8. doi:10.1093/aje/kwp452 20160170
160 Olsen NJ, Angquist L, Larsen SC, . Interactions between genetic variants associated with adiposity traits and soft drinks in relation to longitudinal changes in body weight and waist circumference. Am J Clin Nutr. Sep 2016;104(3):816–26. doi:10.3945/ajcn.115.122820 27465380
161 Palmer JR, Boggs DA, Krishnan S, Hu FB, Singer M, Rosenberg L. Sugar-sweetened beverages and incidence of type 2 diabetes mellitus in African American women. Arch Intern Med. Jul 28 2008;168(14):1487–92. doi:10.1001/archinte.168.14.1487 18663160
162 Partridge SR, McGeechan K, Bauman A, Phongsavan P, Allman-Farinelli M. Improved eating behaviours mediate weight gain prevention of young adults: moderation and mediation results of a randomised controlled trial of TXT2BFiT, mHealth program. Int J Behav Nutr Phys Act. Apr 2 2016;13:44. doi:10.1186/s12966-016-0368-8 27039178
163 Qi Q, Chu AY, Kang JH, . Sugar-sweetened beverages and genetic risk of obesity. N Engl J Med. Oct 11 2012;367(15):1387–96. doi:10.1056/NEJMoa1203039 22998338
164 Romaguera D, Angquist L, Du H, . Food composition of the diet in relation to changes in waist circumference adjusted for body mass index. PLoS One. 2011;6(8):e23384. doi:10.1371/journal.pone.0023384 21858094
165 Schulz M, Kroke A, Liese AD, Hoffmann K, Bergmann MM, Boeing H. Food groups as predictors for short-term weight changes in men and women of the EPIC-Potsdam cohort. J Nutr. Jun 2002;132(6):1335–40. doi:10.1093/jn/132.6.1335 12042455
166 Schulze MB, Manson JE, Ludwig DS, . Sugar-sweetened beverages, weight gain, and incidence of type 2 diabetes in young and middle-aged women. JAMA. Aug 25 2004;292(8):927–34. doi:10.1001/jama.292.8.927 15328324
167 Siqueira JH, Pereira TSS, Moreira AD, . Consumption of sugar-sweetened soft drinks and risk of metabolic syndrome and its components: results of the ELSA-Brasil study (2008-2010 and 2012-2014). J Endocrinol Invest. Jan 2023;46(1):159–171. doi:10.1007/s40618-022-01895-3 35963981
168 Smith JD, Hou T, Ludwig DS, . Changes in intake of protein foods, carbohydrate amount and quality, and long-term weight change: results from 3 prospective cohorts. Am J Clin Nutr. Jun 2015;101(6):1216–24. doi:10.3945/ajcn.114.100867 25854882
169 Stern D, Middaugh N, Rice MS, . Changes in Sugar-Sweetened Soda Consumption, Weight, and Waist Circumference: 2-Year Cohort of Mexican Women. Am J Public Health. Nov 2017;107(11):1801–1808. doi:10.2105/AJPH.2017.304008 28933937
170 Tate DF, Turner-McGrievy G, Lyons E, . Replacing caloric beverages with water or diet beverages for weight loss in adults: main results of the Choose Healthy Options Consciously Everyday (CHOICE) randomized clinical trial. Am J Clin Nutr. Mar 2012;95(3):555–63. doi:10.3945/ajcn.111.026278 22301929
171 Torquati L, Mielke GI, Kolbe-Alexander TL, Brown WJ. Associations between indicators of energy intake and expenditure with excess weight and obesity among women in sedentary and less-sedentary jobs. Prev Med. Jun 2021;147:106507. doi:10.1016/j.ypmed.2021.106507 33667468
172 Tucker LA, Tucker JM, Bailey BW, LeCheminant JD. A 4-year prospective study of soft drink consumption and weight gain: the role of calorie intake and physical activity. Am J Health Promot. Mar-Apr 2015;29(4):262–5. doi:10.4278/ajhp.130619-ARB-315 24717069
173 Vazquez-Duran M, Orea-Tejeda A, Castillo-Martinez L, Cano-Garcia A, Tellez-Olvera L, Keirns-Davis C. A randomized control trial for reduction of caloric and non-caloric sweetened beverages in young adults: effects in weight, body composition and blood pressure. Nutr Hosp. Nov 29 2016;33(6):1372–1378. doi:10.20960/nh.797 28000468
174 Yi SY, Steffen LM, Terry JG, . Added sugar intake is associated with pericardial adipose tissue volume. Eur J Prev Cardiol. Dec 2020;27(18):2016–2023. doi:10.1177/2047487320931303 32594762
175 Pan A, Malik VS, Hao T, Willett WC, Mozaffarian D, Hu FB. Changes in water and beverage intake and long-term weight changes: results from three prospective cohort studies. Int J Obes (Lond). Oct 2013;37(10):1378–85. doi:10.1038/ijo.2012.225 23318721
176 Figueroa R, Saltzman JA, Kang A, Mini FN, Davison KK, Taveras EM. Antenatal dietary concordance among mothers and fathers and gestational weight gain: a longitudinal study. BMC Public Health. Jul 6 2020;20(1):1071. doi:10.1186/s12889-020-09182-7 32631291
177 Guilloty NI, Soto R, Anzalota L, Rosario Z, Cordero JF, Palacios C. Diet, Pre-pregnancy BMI, and Gestational Weight Gain in Puerto Rican Women. Matern Child Health J. Nov 2015;19(11):2453–61. doi:10.1007/s10995-015-1764-4 26100133
178 Lai JS, Soh SE, Loy SL, . Macronutrient composition and food groups associated with gestational weight gain: the GUSTO study. Eur J Nutr. Apr 2019;58(3):1081–1094. doi:10.1007/s00394-018-1623-3 29441408
179 Olafsdottir AS, Skuladottir GV, Thorsdottir I, Hauksson A, Steingrimsdottir L. Maternal diet in early and late pregnancy in relation to weight gain. Int J Obes (Lond). Mar 2006;30(3):492–9. doi:10.1038/sj.ijo.0803184 16331301
180 Renault KM, Carlsen EM, Norgaard K, . Intake of Sweets, Snacks and Soft Drinks Predicts Weight Gain in Obese Pregnant Women: Detailed Analysis of the Results of a Randomised Controlled Trial. PLoS One. 2015;10(7):e0133041. doi:10.1371/journal.pone.0133041 26192183
181 Samano R, Martinez-Rojano H, Ortiz-Hernandez L, . Dietary and Nutrient Intake, Eating Habits, and Its Association with Maternal Gestational Weight Gain and Offspring’s Birth Weight in Pregnant Adolescents. Nutrients. Oct 28 2022;14(21)doi:10.3390/nu14214545
182 Stuebe AM, Oken E, Gillman MW. Associations of diet and physical activity during pregnancy with risk for excessive gestational weight gain. Am J Obstet Gynecol. Jul 2009;201(1):58 e1–8. doi:10.1016/j.ajog.2009.02.025
183 Alderete TL, Wild LE, Mierau SM, . Added sugar and sugar-sweetened beverages are associated with increased postpartum weight gain and soluble fiber intake is associated with postpartum weight loss in Hispanic women from Southern California. Am J Clin Nutr. Sep 1 2020;112(3):519–526. doi:10.1093/ajcn/nqaa156 32597935
184 Cahill JM, Freeland-Graves JH, Shah BS, Lu H, Pepper MR. Determinants of weight loss after an intervention in low-income women in early postpartum. J Am Coll Nutr. Apr 2012;31(2):133–43. doi:10.1080/07315724.2012.10720019 22855919
185 Davis JN, Shearrer GE, Tao W, Hurston SR, Gunderson EP. Dietary variables associated with substantial postpartum weight retention at 1-year among women with GDM pregnancy. BMC Obes. 2017;4:31. doi:10.1186/s40608-017-0166-0 28794888
186 Mahabamunuge J, Simione M, Hong B, . Association of sugar-sweetened beverage intake with maternal postpartum weight retention. Public Health Nutr. Sep 2021;24(13):4196–4203. doi:10.1017/S1368980020005169 33336643