# Summary of conclusion statements and grades

The Committee answered the systematic review question, “What is the relationship between sugar-sweetened beverage consumption and growth, body composition, and risk of obesity?”, with the following conclusion statements.^*^ The grades reflect the strength of the evidence underlying the conclusion statements.

* A conclusion statement is carefully constructed, based on the evidence reviewed, to answer the systematic review question. A conclusion statement does not draw implications and should not be interpreted as dietary guidance.

### Infants, children, and adolescents

Sugar-sweetened beverage consumption by infants, children, and adolescents is associated with unfavorable growth patterns and body composition, and higher risk of obesity in childhood up to early adulthood. This conclusion statement is based on evidence graded as moderate. (Grade: Moderate)

### Adults and older adults

Sugar-sweetened beverage consumption by adults and older adults is associated with unfavorable body composition. This conclusion statement is based on evidence graded as moderate. (Grade: Moderate)

Sugar-sweetened beverage consumption by adults and older adults is associated with higher risk of obesity. This conclusion statement is based on evidence graded as moderate. (Grade: Moderate)

### Individuals during pregnancy and postpartum

A conclusion statement cannot be drawn about the relationship between sugar-sweetened beverage consumption during pregnancy and adequacy of gestational weight gain because there is not enough evidence available, and there are substantial concerns with consistency, precision, risk of bias, directness, and generalizability in the available body of evidence. (Grade: Grade Not Assignable)

A conclusion statement cannot be drawn about the relationship between sugar-sweetened beverage consumption during postpartum and postpartum weight change because there is not enough evidence available. (Grade: Grade Not Assignable)

## Research recommendations

The Committee identified the following research recommendations that describe the research, data, and methodological advances that are needed to strengthen the body of evidence on SSB consumption and growth, body composition, and risk of obesity.

- Measure consumption of SSB with greater specificity and consistency, so that SSB can be assessed separately from other beverages such as 100% juice and LNCSB.
- Utilize stronger assessment and analysis methods, such as well-done substitution models or causal inference models including multi-verse analyses, or empirical p value calibration models that use negative controls
- More research is needed in individuals during pregnancy and postpartum, both in quantity and quality. Future observational studies should include repeated assessment of exposure in these life stages where diet is potentially changing rapidly, as well as consistency in data collection points across studies. Carefully conducted intervention studies also could be very effective in these populations.
- More research is needed on the relationship of SSB to GBCO outcomes in older adults.
- When conducting observational and intervention studies, carefully report TEI, length between exposure and outcomes, and outcome measures used to allow for future systematic reviews with meta-analysis and comparisons between studies.

Table 12 Evidence examining the relationship between sugar-sweetened beverage consumption and growth, body composition, and risk of obesity in infants, children, and adolescents^a^

Study and Population Characteristics | Exposure, Comparator, and Outcome(s) | Results | Confounding and Study Limitations
INFANTS AND YOUNG CHILDREN
Amaro-Rivera, 2019^3^; PCS, U.S. (Puerto Rico); Analytic N=68; Participant characteristics:; - Race and/or ethnicity: Hispanic: 100%; - Maternal education: ≤HS: 32.5%, >HS: 67.5%; - Other SEP measure(s): WIC participation: 100%; - Maternal age: Parent’s age: <30 y: 55.8%, ≥30 y: 44.2%; - Milk feeding practices: EBF for ≥1 mo: 51%, Ever FF: 70.1%, Any BF at ~10 mo: 20.8%; - Child sex (female): 47%; - Birth size: NR; - Gestational age: NR; - Study beverage intake: NR; Excluded from analysis: Excluded participants lost to follow-up | Exposure: SSB; Comparator: Annual change (amounts) in SSB Diet Quality Index Scores (continuous); Exposure Assessment Methods and Timing:; - Interviewer-administered questionnaire completed by caregivers. Diet Quality Index Score based on semi-quantitative FFQ.; - 0-5, 8-36 mo; Outcomes and Assessment Methods:; - WLZ (≥1): Weight and length measured by trained research staff. Weight status assessed using WHO age- and sex-specific WLZ growth charts. Relative risk for WLZ (≥1 z-score versus <1 z-score), with underweight defined as WLZ ≤-2 SD, healthy weight status defined as WLZ >-2 and <1 SD, risk of overweight defined as WLZ between 1-<2, and overweight or obesity defined as WLZ ≥2 SD.; - 11-36 mo (Median: 21 mo, 11-23 mo: 61.0%, 24-36 mo: 39.0%) | [underlined: WLZ (≥1 versus <1)], RR (95% CI) 0.96 (0.76, 1.20) | Model Adjustments: WLZ at baseline; Key confounders accounted for: SEP; sex; race and/or ethnicity; milk feeding practices; baseline anthropometry; Key confounders NOT accounted for: Gestational age; Funding: University of Puerto Rico Central Administration Grant; Capacity Advancement in Research Infrastructure; National Institute on Minority Health and Health Disparities
Chaidez, 2014^12^; PCS, U.S.; Analytic N=56; Participant characteristics (Mean (SD) unless otherwise noted):; - Race and/or ethnicity: Latino: 100%; - Maternal education: 11.1 (4.0) y; - Other SEP measure(s): Monthly household income, median (range): $1,366 ($300-$6,549); Sample “obtained largely through WIC”; - Maternal age: 30.2 (5.6) y; - Milk feeding practices: NR; - Child sex (female): NR; - Birth weight: 3,539 (644) g; - Gestational age: NR; - Study beverage intake: NR; Excluded from analysis: Excluded participants lost to follow-up and participants with missing anthropometric or covariate data | Exposure: Sweetened beverages (did not include 100% fruit juice); Comparator: Sweetened beverages: High (> median) versus Not high (< median); Exposure Assessment Methods and Timing:; - Two 24 h dietary recalls administered to mothers at each time point; - 12-24 mo (baseline), 18-30 mo (mean=27.7; follow-up); Outcomes and Assessment Methods:; - Change in WHZ, BMI z-score, WAZ: Height/length and weight measured by researchers. WHO and CDC growth references used to calculate WHZ, WAZ, and BMI z-score (which reference was used in analysis NR).; - 12-24 mo (baseline), 18-30 mo (mean (SD): 27.7 (3.11) mo) | [underlined: Change in WHZ from 12-24 mo to 27.7 mo, approx 6 mo], β; 0.46, p<0.05; [underlined: Change in WAZ from 12-24 mo to 27.7 mo, approx 6 mo], β; 0.13, p=0.35; [underlined: Change in BMI z-score from 12-24 mo to 27.7 mo, approx 6 mo], β; 0.47, p=0.07 | Model Adjustments: Birth weight, sex, baseline z-score, maternal education, income, indulgent feeding practices, authoritative feeding practices, high fat intake, high added sugar intake; Key confounders accounted for: SEP; sex; race and/or ethnicity; baseline anthropometry; Key confounders NOT accounted for: Milk feeding practices; gestational age; Funding: National Research Initiative of the Cooperative State Research, Education, and Extension Service, USDA; University of California Institute for Mexico and the United States; Western Center for Agricultural Health and Safety; Gustavus and Louise Pfeiffer Research Foundation
Garden, 2011^30^; PCS, Childhood Asthma Prevention Study (CAPS), Australia; Analytic N=362; Participant characteristics (Mean (SD) unless otherwise noted):; - Race and/or ethnicity: Grandparents ethnicity/country of birth: Caucasian: 55%, European: 9%, Middle Eastern: 4%, Indian: 5%, Asian: 4%, Undefined: 24%; - Maternal education: NR; - Other SEP measure(s): Paternal education: ≤10 y: 33%, 11-12 y: 18%, Tertiary education: 48%; - Maternal age: NR; - Milk feeding practices: breastfed ≥6 mo: 42%; - Child sex (female): 49%; - Birth weight: 3,493 (492) g; - Gestational age: NR; - Other relevant characteristics: Secondary analysis of RCT (testing intervention of house dust mite avoidance and omega-3 supplementation); all children recruited at increased risk of developing asthma; - Study beverage intake: Quintiles of grams (g); % total energy intake - Non-milk beverages: 0, 40, 112, 168, 291; 0, 2, 5, 8, 13; Sweetened drinks: 0, 1, 17, 70, 158; 0, 0.002, 1, 4, 8; Excluded from analysis: Excluded participants with missing data on diet or anthropometrics | Exposures: Non-milk beverages (juice, cordial, fruit drinks, and soft drinks), Sweetened drinks (cordial, fruit drinks, and soft drinks); Comparators: Non-milk beverages, Sweetened drinks, continuous (amounts; as quintiles); Exposure Assessment Methods and Timing:; - 3d weighed food records; - 18 mo; Outcomes and Assessment Methods:; - BMI, waist circumference: Weight, length, and waist circumference measured by study nurses; - 8 y | [underlined: BMI], β (95% CI); Non-milk beverages, per quintile g: 0.04 (−0.17, 0.25), p for trend=0.71 % of total energy: 0.07 (−0.14, 0.27), p for trend=0.53; Sweetened drinks, per quintile g: 0.10 (−0.08, 0.29), p for trend=0.27 % of total energy: 0.04 (−0.15, 0.23), p for trend=0.68; [underlined: Waist circumference (cm)], β (95% CI); Non-milk beverages, per quintile g: 0.16 (−0.40, 0.73), p for trend=0.57 % of total energy: 0.19 (−0.36, 0.73), p for trend=0.50; Sweetened drinks, per quintile g: 0.20 (−0.31, 0.70), p for trend=0.44 % of total energy: 0.04 (−0.46, 0.54), p for trend=0.89 | Model Adjustments: Sex, asthma study intervention group, birth weight, breastfed for at least 6mo, parental obesity status, ethnicity, smoking in pregnancy and father’s education, total energy intake (food intake in grams only); Key confounders accounted for: SEP; sex; race and/or ethnicity; milk feeding practices; gestational age; Key confounders NOT accounted for: Baseline anthropometry; Funding: The National Health and Medical Research Council of Australia; Cooperative Research Centre for Asthma; New South Wales Department of Health; Children’s Hospital Westmead; University of Sydney, Faculty of Medicine; Commonwealth Department of Health and Aging
Garden, 2012^31^; PCS, Childhood Asthma Prevention Study (CAPS), Australia; Analytic N=298; Participant characteristics (Mean (SD) unless otherwise noted):; - Race and/or ethnicity: Australian born mother: 74%, Australian born father: 69%; Child’s grandparents ethnicity/country of birth: Caucasian: ~54%, European: ~9%, Middle Eastern/Indian/Asian: ~12%, Undefined: ~25%); - Maternal education: 52% tertiary educated; - Other SEP measure(s): Full-time employment: Mother: 49%, Father: 87%; - Maternal age: 29.0 (5.1) y; - Milk feeding practices: breastfeeding duration: 0 to <3 mo: 40%, 3 to <6 mo: 16.8%, ≥6 mo: 43.2%; - Child sex (female): 49%; - Birth weight: 100% ≥2.5 kg; - Gestational age: 100% ≥36 wk; - Other relevant characteristics: Secondary analysis of RCT (testing intervention of house dust mite avoidance and omega-3 supplementation); all children recruited at increased risk of developing asthma; - Study beverage intake: See results for intake data; Excluded from analysis: Excluded participants who were not still participating in the study at 11.5 y or did not have dietary data. | Exposures: Non-milk beverages (juice, cordial, fruit drinks, and soft drinks), Sweetened drinks (cordial, fruit drinks, and soft drinks); Comparators: Non-milk beverages, Sweetened drinks, continuous (amount); Exposure Assessment Methods and Timing:; - Parent/caregiver completed 3d weighed food record (2 weekdays and 1 weekend day); - 18 mo; Outcomes and Assessment Methods:; - BMI trajectory: Weight and height measured by study nurses. Three BMI trajectories defined using latent basis growth mixture model in relationship to CDC percentiles, stratified by sex.; - 1, 3, 6, 9, 12, 18 mo, 2-5 y (every 6 mo), 8 y, 11.5 y | [underlined: BMI trajectory from birth-11.5 y,] (median intake at 18 mo by trajectory group); Non-milk beverages; Boys: normal trajectory: 128.3 g, early and persistent trajectory: 148.3 g, late BMI increase: 150.9 g, p=0.54; Girls: normal trajectory: 133.3 g, early and persistent trajectory: 139.2 g, late BMI increase: 100.0 g, p=0.50; Sweetened drinks; Boys: normal trajectory: 15.0 g, early and persistent trajectory: 31.7 g, late BMI increase: 17.8 g, p=0.93; Girls: normal trajectory: 21.7 g, early and persistent trajectory: 7.5 g, late BMI increase: 1.0 g, p=0.23; Results analyzed by % of total energy were similar. | Model Adjustments: Dietary intervention group, BF, parental obesity, ethnicity, smoking during pregnancy, father’s education status (multinomial regression only); Key confounders accounted for: SEP; sex; race and/or ethnicity; milk feeding practices; baseline anthropometry (multinomial regression only); Key confounders NOT accounted for: Gestational age; Funding: National Health and Medical Research Council of Australia
Goh, 2022^33^; PCS, National Health Information Database (NHID), Korea; Analytic N=142,668; Participant characteristics (Mean (SD) unless otherwise noted):; - Race and/or ethnicity: NR; - Maternal education: NR; - Other SEP measure(s): Household income (units NR): 11.81 (4.44); - Maternal age: NR; - Milk feeding practices: Type of milk feeding at 4-6 mo: Breast milk: 46.32%, Formula: 32.94%, Mixed milk: 20.35%, Special formula milk: 0.40%; - Child sex (female): 49%; - Birth weight: 3.20 (0.46) kg; - Gestational age: Preterm birth: 3.67%; - Study beverage intake: Boys: ≤200 mL/d: 93.40%, 200-500 mL/d: 6.12%, ≥500 mL/d: 0.48%; Girls: ≤200 mL/d: 94.20%, 200-500 mL:/d: 5.37%, ≥500 mL/d: 0.43%; Excluded from analysis: Excluded participants with missing data on body weight or height, errors on age of measurement, and extreme outliers (BMI ≤4 or ≥50) | Exposure: SSB; Comparator: SSB (continuous, per 1 unit increase): ≤200 mL/d, 200-500 mL/d, ≥500 mL/d; Exposure Assessment Methods and Timing:; - Parental questionnaire; - 18-24 mo; Outcomes and Assessment Methods:; - Early adiposity rebound: Height and weight measured by trained medical staff. Early adiposity rebound defined as rebound of BMI percentile before 4 y. BMI percentile by age and sex was based on WHO Child Growth Standards.; - 4-6 mo, 9-12 mo, 18-24 mo, 30-36 mo, 42-48 mo, 54-60 mo, 66-71 mo | [underlined: Early adiposity rebound (<4 y),] OR SSB at 18-24 mo (per unit); Boys: 1.15, p=0.001; Girls: 1.08, p=0.002 | Model Adjustments: Birth weight, preterm birth, household income; type of feeding milk (4-6 mo); number of weaning food per day, type of feeding milk (9-12 mo); use of salt in food, vitamin supplements (18-24 mo); appetite, number of meals per day, number of snacks per day, daily intake of cow’s milk, daily intake of SSB, parents’ concern about Child’s eating habits (30-36 mo); number of meals per day, daily intake of cow’s milk, daily intake of SSB (42-48 mo); Key confounders accounted for: SEP; sex; milk feeding practices; baseline anthropometry; Key confounders NOT accounted for: Race and/or ethnicity; gestational age; Funding: Dong-A University
Hwang, 2020^41^; PCS, National Health Information Database (NHID), Korea; Analytic N=16,207; Participant characteristics (Mean (SD) unless otherwise noted):; - Race and/or ethnicity: NR; - Maternal education: NR; - Other SEP measure(s): NR; - Maternal age: NR; - Milk feeding practices: Breastfed at 11 mo: Breast milk only: 39.2%, Formula, others at 11 mo: 60.8%; - Child sex (female): 49%; - Birth size: NR; - Gestational age: NR; - Study beverage intake: <200 mL/d: 93.2%, ≥200 mL/d: 6.8%; Excluded from analysis: Excluded participants with less than 5 valid height and weight measurements, birth weight below 0.5 kg or above 5.0 kg, without increasing weight and height during the study, and greater than 3 z-score for weight or height at 69 mo | Exposure: SSB; Comparator: SSB: <200 mL/d versus ≥200 mL/d; Exposure Assessment Methods and Timing:; - Parental questionnaire; - 18-24 mo; Outcomes and Assessment Methods:; - Timing of adiposity rebound: Height and weight measured at primary health clinics and retrieved from a public database (National Health Insurance Service). Very early adiposity rebound defined as <45 mo, early adiposity rebound defined as 57 mo, and moderate to late adiposity rebound as 69 mo.; - 4-6, 9-12, 18-24, 30-36, 42-48, 54-60, 66-71 mo | [underlined: Timing of adiposity rebound], % SSB: <200 versus ≥200 mL/d:; Very early (≤45 mo): 65.1% versus 69.5% Early (57 mo): 15.7% versus 14.0% Moderate-to-late (≥69 mo): 19.2% versus 16.5%; p=0.02 | Model Adjustments: Birth weight, breastfeeding, timing of weaning, SSB at 21 mo, 33 mo, and 45 mo, add salt to baby’s food, meal with parents, having breakfast, screen time, exercise habit, family history of metabolic syndrome; Key confounders accounted for: Sex; milk feeding practices; baseline anthropometry; Key confounders NOT accounted for: SEP; race and/or ethnicity; gestational age; Funding: Kangdong Sacred Heart Hospital Fund
Leermakers, 2015a^55^; PCS, Generation R, Netherlands; Analytic N=1,639; Participant characteristics (Mean (SD) unless otherwise noted):; - Race and/or ethnicity: Dutch: 100%; - Maternal education: Education level: Lower (secondary school or lower): ~34%, Higher: ~66%; - Other SEP measure(s): NR; - Maternal age: ~32 y; - Milk feeding practices: Breastfeeding duration (median): 3.5 mo; Any breastfeeding at 13 mo: 6.8%; - Child sex (female): 50%; - Birth size: NR; - Gestational age: NR; - Study beverage intake: Mean intake: 7.1 svg/wk (boys), 7.0 svg/wk (girls); Excluded from analysis: Excluded participants with missing data on SSB intake at 13 mo and without follow-up at 6y. | Exposure: Sugar-containing beverages, including fruit juices, fruit concentrates, lemonades, soft drinks, and sports drinks; Comparator: Sugar-containing beverage intake tertiles: High, Medium, Low (reference); Exposure Assessment Methods and Timing:; - Caregiver FFQ; - 13 mo; Outcomes and Assessment Methods:; - Preperitoneal fat: Preperitoneal fat measured via abdominal ultrasound; - 6 y | [underlined: Preperitoneal fat], coefficient (95% CI) Total population; Medium versus low tertile (ref): −0.05 (−0.15, 0.05); High versus low tertile (ref): 0.02 (−0.08, 0.12); p-trend: 0.63 Boys; Medium versus low tertile (ref): −0.06 (−0.19, 0.07); High versus low tertile (ref): −0.06 (−0.19, 0.08); p-trend: 0.41 Girls; Medium versus low tertile (ref): −0.05 (−0.18, 0.09); High versus low tertile (ref): 0.10 (−0.04, 0.24); p-trend: 0.15 | Model Adjustments: Age at measurements, total energy intake, child sex (total population analysis only), maternal age, BMI, education level, smoking during pregnancy, folic acid supplement use during pregnancy, breastfeeding of the child, diet quality score, hours of TV watching at age 2; Key confounders accounted for: SEP; sex; race and/or ethnicity; milk feeding practices; Key confounders NOT accounted for: Gestational age; baseline anthropometry; Funding: Erasmus Medical Centre; Erasmus University Rotterdam; Netherlands Organization for Health Research and Development
Leermakers, 2015b^54^; PCS, Generation R, Netherlands; Analytic N=2,371 (height, weight, BMI SDS, overweight), 2,001; Participant characteristics (Mean (SD) unless otherwise noted):; - Race and/or ethnicity: Dutch: 100%; - Maternal education: Education level: Lower (only primary/secondary school): 34.5%, Higher: 65.5%; - Other SEP measure(s): Net household income: <2,200 Euros/mo: 20.3%, >2,200 Euros/mo: 79.7%; - Maternal age: 31.9 (4.2) y; - Milk feeding practices: Never Breastfed: 9.6%, Partially Breastfed in the first 4 mo: 60.6%, exclusively breastfed at least 4 mo: 28.8%; - Child sex (female): 50%; - Birth weight: 3,492 (574) g; - Gestational age: Median (95% range): 40.1 (35.9, 42.3); - Study beverage intake: Overall (median (95% range)): 7 (0-26) svg/wk; High tertile (median): 14.9 svg/wk, Medium tertile (median): 8.0 svg/wk, Low tertile (median): 3.1 svg/wk; Excluded from analysis: Excluded participants with missing data on SSB intake at 13 mo, BMI at any time point, and (for total body fat percentage and android/gynoid fat ratio) DXA measurements. | Exposure: Sugar-containing beverages, including fruit juices, fruit concentrates, lemonades, soft drinks, and sports drinks; Comparator: Sugar-containing beverage intake tertiles: High (median=15 svg/wk), Medium (median=8 svg/wk), Low (median=3 svg/wk; ref); 1 svg = 150 mL; Exposure Assessment Methods and Timing:; - Caregiver FFQ; - 13 mo; Outcomes and Assessment Methods:; - Height, weight, BMI SDS, total body fat percentage, android/gynoid fat ratio, overweight/obesity: Height, weight and body fat measured by trained staff. Body fat measured using DXA. Age- and sex- specific BMI SDS obtained using Dutch reference growth curves. Age- and sex- specific SDS calculated for android/gynoid fat mass ratio. Overweight classified according to age- and sex- specific cutoff points from IOTF.; - 2, 3, 4, 6 y | [underlined: Weight SDS], coefficent (95% CI) Boys; Medium versus low intake (ref): −0.03 (−0.12, 0.06); High versus low intake (ref): 0.03 (−0.06, 0.12); p-trend: 0.54 Girls; Medium versus low intake (ref): 0.01 (−0.08, 0.10); High versus low intake (ref): 0.07 (−0.01, 0.16); p-trend: 0.09; [underlined: Height SDS], coefficent (95% CI) Boys; Medium versus low intake (ref): 0.13 (−0.01, 0.27); High versus low intake (ref): 0.14 (0.00, 0.27), p<0.05; p-trend<0.05; Girls; Medium versus low intake (ref): −0.02 (−0.17, 0.13); High versus low intake (ref): 0.09 (−0.05, 0.23); P-trend: 0.19; [underlined: BMI SDS], coefficent (95% CI) Boys; 2 y: Medium versus low intake (ref): −0.02 (− 0.15, 0.11); 2 y: High versus low intake (ref): −0.01 (−0.15, 0.12); p-trend: 0.85; 3 y: Medium versus low intake (ref): −0.07 (− 0.19, 0.06); 3 y: High versus low intake (ref): −0.01 (−0.15, 0.12); p-trend: 0.84; 4 y: Medium versus low intake (ref): −0.04 (− 0.15, 0.07); 4 y: High versus low intake (ref): −0.01 (−0.12, 0.09); p-trend: 0.82; 6 y: Medium versus low intake (ref): −0.02 (− 0.14, 0.10); 6 y: High versus low intake (ref): 0.05 (−0.08, 0.18); p-trend: 0.42; Girls; 2 y: Medium versus low intake (ref): 0.03 (−0.12, 0.16); 2 y: High versus low intake (ref): 0.15 (0.01, 0.30), p<0.05; p-trend: 0.03; 3 y: Medium versus low intake (ref): 0.05 (−0.07, 0.17); 3 y: High versus low intake (ref): 0.14 (0.01, 0.27), p<0.05; p-trend: 0.03; 4 y: Medium versus low intake (ref): −0.01 (− 0.12, 0.10); 4 y: High versus low intake (ref): 0.13 (0.01, 0.25), p<0.05; p-trend: 0.03; 6 y: Medium versus low intake (ref): 0.01 (−0.11, 0.13); 6 y: High versus low intake (ref): 0.11 (0.00, 0.23), p<0.05; p-trend: 0.04; [underlined: BMI SDS trajectory from 13 mo to 6 y]; Boys; Medium versus low intake (ref): Data NR, NS High versus low intake (ref): Data NR, NS; Girls; Medium versus low intake (ref): Data NR, NS High versus low intake (ref): Data NR, NS; [underlined: Total body fat percentage], coefficent (95% CI); Boys; Medium versus low intake (ref): −0.07 (−0.22, 0.08); High versus low intake (ref): 0.05 (−0.11, 0.20); p-trend: 0.53; Girls; Medium versus low intake (ref): −0.02 (−0.17, 0.12); High versus low intake (ref): 0.09 (−0.06, 0.23); p-trend: 0.25; [underlined: Android/gynoid fat ratio], coefficent (95% CI); Boys; Medium versus low intake (ref): 0.00 (−0.16, 0.16); High versus low intake (ref): 0.02 (−0.14, 0.18); p-trend: 0.77; Girls; Medium versus low intake (ref): 0.08 (−0.08, 0.23); High versus low intake (ref): 0.14 (−0.02, 0.29); p-trend: 0.09; [underlined: Risk of overweight/obesity], OR (95% CI); Boys; 2 y: Medium versus low intake (ref): 0.86 (0.43, 1.74); 2 y: High versus low intake (ref): 1.09 (0.57, 2.11); p-trend: 0.77; 3 y: Medium versus low intake (ref): 0.78 (0.38, 1.60); 3 y: High versus low intake (ref): 0.71 (0.34, 1.48); p-trend: 0.36; 4 y: Medium versus low intake (ref): 0.78 (0.38, 1.57); 4 y: High versus low intake (ref): 0.51 (0.23, 1.13); p-trend: 0.10; 6 y: Medium versus low intake (ref): 1.03 (0.57, 1.88); 6 y: High versus low intake (ref): 0.90 (0.44, 1.85); p-trend: 0.75; Girls; 2 y: Medium versus low intake (ref): 1.12 (0.61, 2.03); 2 y: High versus low intake (ref): 1.40 (0.76, 2.56); p-trend: 0.27; 3 y: Medium versus low intake (ref): 1.56 (0.82, 2.94); 3 y: High versus low intake (ref): 1.48 (0.79, 2.77); p-trend: 0.25; 4 y: Medium versus low intake (ref): 0.95 (0.48, 1.87); 4 y: High versus low intake (ref): 1.24 (0.68, 2.23); p-trend: 0.45; 6 y: Medium versus low intake (ref): 1.09 (0.67, 1.78); 6 y: High versus low intake (ref): 1.27 (0.78, 2.06); p-trend: 0.34 | Model Adjustments: Age at measurements, gestational age at birth, birth weight (SDS), age of mother and father, net household income, maternal BMI, education, smoking, folic acid use, pre-pregnancy and pregnancy related comorbidities, child hospitalization in first year of life, history of allergy to cow’s milk, Child’s intake of sugar, confectionary, cakes and pastry, breastfeeding, age at introduction of complementary feeding, total energy intake, hours of television watching; Key confounders accounted for: SEP; sex; race and/or ethnicity; milk feeding practices; gestational age; Key confounders NOT accounted for: Baseline anthropometry; Funding: Erasmus Medical Centre; Erasmus University Rotterdam; Netherlands Organization for Health Research and Development
Lewis, 2020^56^; PCS, U.S.; Analytic N=2,735; Participant characteristics (Mean (SD) unless otherwise noted):; - Race and/or ethnicity: Non-Hispanic White: ~35%, Hispanic: ~30% African- American: ~27%, Other: ~8%; - Maternal education: NR; - Other SEP measure(s): NR; - Maternal age: NR; - Milk feeding practices: NR; - Child sex (female): ~50%; - Birth size: NR; - Gestational age: NR; - Study beverage intake: <1x/wk: ~51%, Several/wk: ~10%, 1/d: ~17%, 2x/d: ~11%, ≥3x/d: ~10%; Excluded from analysis: Excluded participants with highest 1% of health care utilization (>12 visits/y), pregnant girls, missing data on sugary drink intake, and fewer than 2 plausible height/weight measures. | Exposure: Sugary drinks, including 100% fruit juice and sugar-sweetened beverages (fruit-flavored drinks, juice from concentrate, punch, KoolAid, soda, sports drinks, sweet tea or flavored milks); Comparator: Sugary drinks: < once/wk (ref), Several/wk, 1/d, 2 times/d, ≥3 times/d; Exposure Assessment Methods and Timing:; - Caregiver completed dietary screener; - 6 mo to <2y; Outcomes and Assessment Methods:; - BMI z-score: Height and weight extracted from electronic health record. BMI z-score were based on WHO (children <2 y at any time at follow-up) and CDC standards (children >2 y for all of follow-up).; - 6 mo to 17 y | [underlined: Change in BMI z-score per y], β (95% CI) Several/wk versus ≤ 1x/wk (ref): −0.23 (−0.58, 0.13); 1x/d versus ≤once/wk (ref): −0.23 (−0.51, 0.05); 2x/d versus ≤once/wk (ref): −0.001 (−0.34, 0.34); ≥3x/d versus ≤once/wk (ref): −0.03 (−0.40, 0.33) | Model Adjustments: Age, age squared, sex, race, clinic site, visit type where sugary drink screening took place, inverse of total follow-up time, number of visits during follow-up, baseline BMI z-score; Key confounders accounted for: Sex; race and/or ethnicity; baseline anthropometry; Key confounders NOT accounted for: SEP; milk feeding practices; gestational age; Funding: Healthy Eating Research from Robert Wood Johnson Foundation
Li, 2008^57^; PCS, Infant Feeding Practices Study II (IFPS II), U.S.; Analytic N=1,187; Participant characteristics (Mean (SD) unless otherwise noted):; - Race and/or ethnicity: White: 86%, Hispanic: 5%, Black: 4%, Another race/ethnicity: 4%; - Maternal education: College degree: 46%; - Other SEP measure(s): Income as percentage of federal poverty index: ~275%; - Maternal age: 29.6 (5.3) y; - Milk feeding practices: BF intensity 0-6 mo (% of breast milk feeds among all milk feeds): Low (<20%): 35.9%, Medium (20- 80%): 18.6%, High (>80%): 45.5%; - Child sex (female): ~51%; - Birth weight: ~3.4 kg; - Gestational age: ~39.4 wk; 100% born ≥35 wk gestation; - Study beverage intake: ~0.02 sweet drinks/d; Excluded from analysis: Excluded participants without any weight measurements during the second half of infancy, with impossible age reversals, with missing data on BF intensity, who were EBF at the breast, with missing data on bottle-emptying behaviors, or missing data on covariates. | Exposure: Sweet drinks (servings of juice drinks, soft drinks, sodas, sweet tea, Kool-Aid, etc.) during the first half of infancy; Comparator: Sweet drinks: Continuous (feedings/d); Exposure Assessment Methods and Timing:; - Maternal surveys; - 1, 2, 3, 4, 5, 6, 7, 9, 10.5, 12 mo; Outcomes and Assessment Methods:; - Excess weight (WAZ): Weight and age at most recent doctor’s visit reported by mother. WAZ calculated using CDC reference data. WAZ dichotomized at ≤1 (normal weight) and >1 z-score (excess weight).; - 7 mo, 12 mo (Mean (SD): 10.87 (2.31) mo) | [underlined: Excess weight (≥1 versus <1 WAZ)], OR (95% CI); 1.98 (0.59, 6.65) | Model Adjustments: Breastfeeding intensity, frequency of infant-initiated bottle emptying, frequency of maternal encouragement of infant bottle emptying, sex, gestational age, age at last weight measurement, birth weight, age when solid food was first indicated (sweet drinks only), sweet drinks over the first half of infancy (solid foods only), maternal age, parity, maternal education, race/ethnicity, income as percentage of federal poverty level, maternal BMI before pregnancy, maternal smoking at 3 mo postpartum; Key confounders accounted for: SEP; sex; race and/or ethnicity; milk feeding practices; gestational age; Key confounders NOT accounted for: Baseline anthropometry; Funding: FDA; CDC; Office of Women’s Health (HHS); NIH; Maternal and Child Health Bureau (HHS)
Mahoney, 2018^63^; PCS, Born in Bradford 1000, U.K.; Analytic N=722 (12 mo); 779 (18 mo); Participant characteristics (Mean (SD) unless otherwise noted):; - Race and/or ethnicity: Pakistani: ~56%, White British: ~44%; - Maternal education: NR; - Other SEP measure(s): NR; - Maternal age: NR; - Milk feeding practices: NR; - Child sex (female): NR; - Birth weight: 3,234.15 (521.97) g; - Gestational age: NR; - Study beverage intake: Frequency at 12, 18 mo, respectively (Median, IQR): 0.0 (0.0, 0.5) times/wk, 7.0 (0.0, 14.0) times/wk; Excluded from analysis: Excluded participants with multiple births, missing child dietary data or outcome data, and not of White British or Pakistani ethnicity | Exposure: Sugar-sweetened drinks; Comparator: Sugar-sweetened drinks, Consumer versus non-consumer at 12 mo, ≤ versus > Median frequency at 18 mo; Exposure Assessment Methods and Timing:; - FFQ completed by parents; - 12, 18 mo; Outcomes and Assessment Methods:; - BMI z-score: Height, weight measured by trained researchers. Age- and sex- adjusted BMI calculated based on WHO 2006 standards.; - 36 mo | [underlined: BMI z-score], β (95% CI); Intake at 12 mo: Consumer versus non- consumer: 0.07 (−0.08, 0.23), p=0.36; Intake at 18 mo: > versus ≤ 7.0/wk: −0.01 (−0.18, 0.16), p=0.91 | Model Adjustments: Ethnicity, gender, birth weight, other key indicator food groups (formula milk; commercial savoury baby foods; commercial sweet baby foods; chips, roast and potato shapes; processed meat products; vegetables; fruit; cakes, biscuits, chocolate and sweets; crisps and savoury snacks; sugar-sweetened drinks; pure fruit juice; low-sugar drinks; water); Key confounders accounted for: Sex; race and/or ethnicity; Key confounders NOT accounted for: SEP; milk feeding practices; gestational age; baseline anthropometry; Funding: NIHR
Pan, 2014^75^; PCS, Infant Feeding Practices Study II (IFPS II), U.S.; Analytic N=1,189; Participant characteristics (Mean (SD) unless otherwise noted):; - Race and/or ethnicity: White, non- Hispanic: 88.0%, Hispanic: 4.8%, Other, non-Hispanic: 3.9%, Black, non-Hispanic: 3.4%; - Maternal education: HS or less: 16.1%, Some college: 34.8%, College graduate: 49.0%; - Other SEP measure(s): Income-to-poverty ratio: <185%: 33.6%, 185%-349%: 37.9%, ≥350%: 28.5%; - Maternal age: 18-24 y: 13.5%, 25-29 y: 33.2%, 30-34 y: 32.3%, ≥20.9%; - Milk feeding practices: breastfed <6 mo: 48.6%, breastfed ≥6 mo: 51.4%; - Child sex (female): 50%; - Birth weight: ≤4,000 g: 87.1%, >4,000 g: 12.9%; - Gestational age: NR; - Study beverage intake: SSB intake at 10- 12 mo: No SSB: 83.3%, <1 time/wk: 4.6%, 1-<3 times/wk: 6.1%, ≥3 times/wk: 6.0%; Excluded from analysis: Excluded participants that were lost to follow-up, were >13 mo at IFPS II survey, did not have anthropometric measurements at 6 y, had height, weight, or BMI at follow-up that was biologically implausible, or did not have data on SSB. | Exposure: SSB (juice drinks, soft drinks, soda, sweet tea, Kool-Aid [Kraft foods, West Plains, NY]); Comparator: SSB at 10-12 mo: No SSB (ref), <1 time/wk, 1-<3 times/wk, ≥3 times/wk; Exposure Assessment Methods and Timing:; - Maternal questionnaire; - 10, 12 mo; Outcomes and Assessment Methods:; - Obesity: Height and weight measured and reported by mothers; given instructions in questionnaire on how to complete measurements. Obesity defined as gender-specific BMI-for-age ≥95th percentile according to 2000 CDC growth charts; - 6 y | [underlined: Obesity], OR (95% CI); Amount of SSBs consumed from 10-12 mo <1 time/wk versus none (ref): 1.64 (0.65, 4.14); 1-<3 times/wk versus none (ref): 1.51 (0.65, 3.48); ≥3 times/wk versus none (ref): 2.00 (1.02, 3.90) | Model Adjustments: Gender, birth weight, age at solid food introduction, breastfeeding duration, maternal age, maternal race/ethnicity, maternal education, marital status, income-to-poverty ratio, pre-pregnancy weight status; Key confounders accounted for: SEP; sex; race and/or ethnicity; milk feeding practices; Key confounders NOT accounted for: Gestational age; baseline anthropometry; Funding: FDA; CDC; Office of Women’s Health; NIH; Maternal and Child Health Bureau
Quah, 2019^78^; PCS, Growing Up in Singapore Towards healthy Outcomes (GUSTO), Singapore; Analytic N=555; Participant characteristics (Mean (SD) unless otherwise noted):; - Race and/or ethnicity: Chinese: ~60%, Malay: ~28%, Indian: ~12%; - Maternal education: Post-secondary and below: ~63%, University and above: ~37%; - Other SEP measure(s): NR; - Maternal age: ~31 y; - Milk feeding practices: Never breastfed: ~3%, breastfed < 6 mo: ~85%, breastfed ≥6 mo: ~12%; - Child sex (female): ~49%; - Birth weight for gestational age z-score: ~0.09; - Gestational age: NR; - Study beverage intake: Tertiles, median (IQR): high: 138 (96-231) mL, medium: 28 (18-43) mL, low: 2 (0-6) mL; Excluded from analysis: Excluded participants without FFQ or BMI data. | Exposure: SSB (carbonated, non- carbonated drinks, and prepackaged fruit juices containing added sugar; malted drinks; cultured milk drinks; soya-based drinks; traditional drinks (i.e., barley water, chrysanthemum tea, herbal tea)); Comparator: SSB, Continuous (per 100 ml/d), Tertiles: high intake, medium intake, versus low intake (ref); Exposure Assessment Methods and Timing:; - Self-administered FFQ completed by primary caregiver (mostly mothers); - 18 mo; Outcomes and Assessment Methods:; - BMI z-score, sum of skinfold thickness, overweight/obesity: Weight, height, and skinfold thicknesses (triceps, biceps, subscapular, and supra-iliac) measured by trained staff. Sum of skinfolds is sum of 4 averages. Sex- and age-specific BMI z- score calculated using WHO references, with overweight and obesity defined as +1 SD above reference distribution.; - 6 y | [underlined: BMI z-score], β (95% CI); Continuous (per 100 mL/d): 0.05 (−0.01, 0.11), p>0.05; Medium versus Low intake (ref): −0.05 (−0.29, 0.19), p>0.05; High versus Low intake (ref): 0.06 (−0.20, 0.31), p>0.05; p-trend: 0.676; [underlined: Sum of skinfold thickness], RR (95% CI) Continuous (per 100 mL/d): 0.71 (−0.05, 1.47), p>0.05; Medium versus Low intake (ref): −0.92 (−3.59, 1.75), p>0.05; High versus Low intake (ref): −0.46 (−3.27, 2.34), p>0.05; p-trend: 0.850; [underlined: Overweight/obesity], RR (95% CI); Continuous (per 100 mL/d): 1.09 (1.02, 1.17), p<0.05; Medium versus Low intake (ref): 0.93 (0.55, 1.58), p>0.05; High versus Low intake (ref): 1.10 (0.67, 1.81), p>0.05; p-trend: 0.204 | Model Adjustments: Maternal ethnicity, maternal education level, birth weight for gestational age, screen time, breastfeeding duration, parity, energy intake at 18 mo; Key confounders accounted for: SEP; sex; race and/or ethnicity; milk feeding practices; baseline anthropometry; Key confounders NOT accounted for: Gestational age; Funding: Singapore National Research Foundation; Singapore Institute for Clinical Sciences; Agency for Science, Technology and Research
Sonneville, 2015^84^; PCS, Project Viva, U.S.; Analytic N=1,163; Participant characteristics (Mean (SD) unless otherwise noted):; - Race and/or ethnicity: White: 70%, Black: 12%, Other: 11%, Hispanic: 4%, Asian: 3%; - Maternal education: College graduate: 73%; - Other SEP measure(s): Household income: >$70k/y: 65%; - Maternal age: 32.4 (4.9) y; - Milk feeding practices: breastfeeding duration: 6.4 (4.5) mo; - Child sex (female): 50%; - Birth size: NR; - Gestational age: NR; - Study beverage intake: None: 22.6%, 1-7 fl oz/d: 53.2%, 8-15 fl oz/d: 20.2%, ≥16 fl oz/d: 4.0%; Excluded from analysis: Excluded participants without in-person visits at early and middle-childhood | Exposure: Fruit juice (not defined as 100%); Comparator: Fruit juice (not defined as 100%): None (ref), 1-7 fl oz/d, 8-15 fl oz/d, ≥16 fl oz/d; Exposure Assessment Methods and Timing:; - Maternal questionnaire; - 1 y; Outcomes and Assessment Methods:; - BMI z-score: Height and weight measured by study personnel. BMI z- score calculated using age- and sex- specific z-scores using US reference growth data; - 3.1 y, 7.7 y | [underlined: BMI z-score], β (95% CI); 3.1 y; 1-7 oz/d versus None (ref): 0.03 (−0.10, 0.15); 8-15 oz/d versus None (ref): 0.17 (0.01, 0.33); >16 oz/d versus None (ref): 0.30 (−0.01, 0.61) p=0.07; 7.7 y; 1-7 oz/d versus None (ref): 0.07 (−0.06, 0.21); 8-15 oz/d versus None (ref): 0.23 (0.05, 0.40); >16 oz/d versus None (ref): 0.27 (−0.05, 0.59); p=0.05 | Model Adjustments: Maternal age, education, pre- pregnancy BMI, household income, child age, sex, race/ethnicity, weight-for-length z- score at 1 year, energy intake, juice and water intake at 1 y; Key confounders accounted for: SEP; sex; race/ethnicity; baseline anthropometry; Key confounders NOT accounted for: Milk feeding practices; gestational age; Funding: CDC, NIH, Harvard Medical School, Harvard Pilgrim Health Care Foundation
Vandyousefi, 2021^91^; PCS, Study of Women, Infant Feeding and Type 2 Diabetes after gestational diabetes mellitus pregnancy (SWIFT), U.S.; Analytic N=835; Participant characteristics (Mean (SD) unless otherwise noted):; - Race and/or ethnicity: Non-Hispanic Asian: 37%, Hispanic: 30%, Non-Hispanic White: 23%, Non-Hispanic Black: 8%, Mixed race/other: 2%; - Maternal education: 14.9 (2.9) y; - Other SEP measure(s): Private insurance: 100%; WIC recipient: 25%; - Maternal age: 33.4 (4.8) y; - Milk feeding practices: Any BF duration: 9 (7.2) mo; breastfeeding duration <6 mo: 40%, ≥6 mo: 60%; Breastfeeding intensity at 6-9 wk: Exclusively breastfed: 22%, Mostly breastfed: 41%, Mixed/inconsistent formula-fed: 21%, Exclusively or mostly formula-fed: 16%; breastfeeding intensity and duration at 12 mo: <6: 53%, ≥6: 47%; - Child sex (female): 48%; - Birth weight: 3,397 (499) g; Birth length: 50.5 (2.4) cm; Size-at-birth percentile: LGA: 21%, AGA: 77%, SGA: 2%; - Gestational age: 39 (1.2) wk; - Other relevant characteristics: GDM: 100%; - Study beverage intake: Beverage intake from birth to 1 y: No SSB/no 100% fruit juice: 33%, 100% fruit juice: 51%, SSB: 16%; Excluded from analysis: Excluded participants with missing data on BF, infant dietary intake variables from birth to 1 y, sociodemographics, prenatal and newborn clinical outcomes, and child weight and height measures at 2-5 y, and mothers who had overt diabetes at study baseline. | Exposure: SSB (any sugary drinks, Pedialyte, water or juices with added sugar), 100% fruit juice; (unsweetened/with no added sugar); Comparator: 100% fruit juice only, SSB only, SSB or 100% fruit juice, no SSB/100% juice intake (ref); Exposure Assessment Methods and Timing:; - Maternal surveys of date of introduction of solids, fruit juice, sweetened beverages, water, sugar water, and other beverages, including types and amounts of each item; - 6-9 wk, 1 y, 2 y post baseline (in-person surveys); Monthly from delivery to 1 y (mailed surveys); Outcomes and Assessment Methods:; - Overweight, Obesity: Weight and length obtained from Electronic Health Records during well check visits. Age- and sex- standardized BMI percentiles calculated based on CDC growth percentiles. Overweight defined as BMI-for-age 85th-<95th percentile. Obesity defined as BMI- for-age ≥95th percentile.; - 2-5 y (Mean (SD): 50.5 (6.3) mo) | [underlined: Overweight], OR (95% CI); 100% fruit juice versus No SSB/no 100% fruit juice (ref) from birth to 1 y: 1.24 (0.78, 1.98), p=0.48; SSB versus No SSB/no 100% fruit juice (ref) from birth to 1 y: 1.31 (0.69, 2.50), p=0.67; [underlined: Obesity], OR (95% CI); 100% fruit juice versus No SSB/no 100% fruit juice (ref) from birth to 1 y: 2.18 (1.17, 4.06), p=0.02; SSB versus No SSB/no 100% fruit juice (ref) from birth to 1 y: 3.22 (1.55, 6.67), p<0.01; [underlined: Overweight, Adequate breastfeeding], OR (95% CI)); 100% fruit juice versus No SSB/no 100% fruit juice (ref) from birth to 1 y: 1.23 (0.73, 2.34), p=0.65; SSB versus No SSB/no 100% fruit juice (ref) from birth to 1 y: 1.31 (0.51, 2.94), p=0.65 SSB or 100% fruit juice versus No SSB/No 100% fruit juice (ref) from birth to 1 y: 1.28 (0.71, 2.18), p=0.38; [underlined: Obesity, Adequate breastfeeding], OR (95% CI); 100% fruit juice versus No SSB/no 100% fruit juice (ref) from birth to 1 y: 3.13 (1.11, 7.29), p=0.03; SSB versus No SSB/no 100% fruit juice (ref) from birth to 1 y: 3.35 (1.32, 8.50), p=0.01 SSB or 100% fruit juice versus No SSB/No 100% fruit juice (ref) from birth to 1 y: 3.32 (1.29, 8.25), p<0.01; [underlined: Overweight, Adequate exclusive breastfeeding], OR (95% CI); 100% fruit juice versus No SSB/no 100% fruit juice (ref) from birth to 1 y: 1.28 (0.73, 2.27), p=0.39; SSB versus No SSB/no 100% fruit juice (ref) from birth to 1 y: 1.26 (0.73, 2.18), p=0.72 SSB or 100% fruit juice versus No SSB/No 100% fruit juice (ref) from birth to 1 y: 1.05 (0.55, 1.99), p=0.43; [underlined: Obesity, Adequate exclusive breastfeeding] OR (95% CI); 100% fruit juice versus NO SSB/no 100% fruit juice (ref) from birth to 1 y: 4.17 (1.55, 11.17), p<0.01; SSB versus No SSB/no 100% fruit juice (ref) from birth to 1 y: 4.71 (1.43, 15.01), p<0.01 SSB or 100% fruit juice versus No SSB/No 100% fruit juice (ref) from birth to 1 y: 4.45 (1.40, 8.47), p<0.01 | Model Adjustments: Maternal education level, race/ethnicity, gestational weight gain, prenatal 3 h 100 g OGTT sum of 4 z-scores, GDM treatment type, gestational age at GDM diagnosis, WIC participation, parity, infant sex, infant size for gestational age, sex at birth, and age at BMI measurement; Key confounders accounted for: SEP; sex; race and/or ethnicity; milk feeding practices; Key confounders NOT accounted for: Gestational age; baseline anthropometry; Funding: NIDDK; NICHD; ADA
Wu, 2021^101^; PCS, Project Viva, U.S.; Analytic N=783; Participant characteristics (Mean (SD) unless otherwise noted):; - Race and/or ethnicity: White: 67%, Black: 14%, Other: 13%, Hispanic: 4%, Asian: 3%; - Maternal education: Maternal college degree or higher: 72%; - Other SEP measure(s): Median household income at birth: ~$58,900; - Maternal age: NR; - Milk feeding practices: NR; - Child sex (female): 51%; - Birth size: NR; - Gestational age: NR; - Study beverage intake: 1.4 (1.5) svg/d; Excluded from analysis: Excluded participants without data on juice intake, and with missing outcome data at either time point | Exposure: Fruit juice (not defined as 100%); Comparator: Fruit juice (not defined as 100%), continuous, per 4 oz servings/d; Exposure Assessment Methods and Timing:; - Maternal questionnaire; - 1 y; Outcomes and Assessment Methods:; - Visceral adipose tissue (VAT), subcutaneous abdominal adipose tissue (SAAT), and total abdominal adipose tissue (TAAT): VAT, SAAT, and TAAT area measured by DXA. Transformed to internal, sex-specific SDS.; - Mid-childhood - 7.8 (0.7) y, early adolescence - 13.0 (0.8) y | [underlined: VAT area (SDS)], β (95% CI); Overall: 0.08 (0.03, 0.13), p=0.001 (interaction with sex: p=0.46); Boys: 0.08 (0.00, 0.15); Girls: 0.05 (−0.01, 0.11); [underlined: SAAT area (SDS)], β (95% CI); Overall: 0.05 (0.00, 0.09), p=0.04 (interaction with sex: p=0.03); Boys: 0.03 (−0.03, 0.10); Girls: 0.03 (−0.03, 0.08); [underlined: TAAT area (SDS)], β (95% CI); Overall: 0.05 (0.01, 0.10), p=0.01 (interaction with sex: p=0.05); Boys: 0.04 (−0.02, 0.10); Girls: 0.03 (−0.02, 0.09) | Model Adjustments: Age at outcome, child sex, race/ethnicity, age at baseline, baseline BMI z-score, maternal pre-pregnancy BMI, education, prenatal sugar-sweetened beverage intake, paternal BMI, median household income at birth; Key confounders accounted for: SEP; sex; race/ethnicity; baseline anthropometry; Key confounders NOT accounted for: Milk feeding practices; gestational age; Funding: NIH
CHILDREN AND ADOLESCENTS, RANDOMIZED CONTROLLED TRIALS
de Ruyter, 2012^15^ (see Katan 2016^46^) RCT-Parallel, Kids (DRINK), Netherlands; Baseline N=641, Analytic N=477 (Attrition: 26%); Power: sample size calculation is 212 subjects per treatment, power=0.8; α=0.05; Included in meta-analysis: Yes; Participant characteristics at baseline:; children who commonly drank SSBs; - Age: 8.2 (1.8)y; - Female: 47%; - Race/ethnicity: “most” were White; ~78% Dutch ancestry; ~22% Non-Western ancestry; - SEP: Parent education: ~55% college or university degree; ~33% high school diploma; ~14% elementary, vocational; - Anthropometry: BMI ~16.9 kg/m^2^; - Physical activity: NR; - Diet quality: NR; - TEI: NR; - Study beverage intake at baseline: SSBs in classroom at 10am break: 1.02 (0.20); SSB/weekend day: 1.50 (1.40); Excluded from Study or Analysis: did not commonly drink sugar-sweetened beverages (<250 mL/d on at least 3 of 5 school days); <5y at baseline; medication or medical treatment for obesity; diabetes, growth disorders, celiac disease, serious gastroenterologic diseases (e.g., inflammatory bowel disease); medical history or surgery known to interfere with study; participation in another intervention study up to 3 months before and during DRINK if it interfered with study; physical disabilities that interfere with measurements; plans to relocate and change schools; attending a school that was difficult to reach or had few prospective participants; | Intervention: Sugar-containing, non- carbonated beverage; 1 can/d provided (8oz, 250 mL/d), n = 322; Note: custom drinks were developed for this study to ensure that the sugar-free and sugar-containing drinks tasted and looked essentially the same; drinks contained 0 or 26 g of sucrose (0 or 104 kcal per day). The sugar-free beverages contained 34 mg of sucralose and 12 mg of acesulfame potassium per can; Comparator: Artificially-sweetened, non- carbonated beverage; 1 can/d provided (8oz, 250 mL/d), n = 319; Study Duration: 18mo; Compliance: calculated adherence rate per child during school days from the number of cans returned empty, half- filled, or full during one randomly selected week each month; 26% of participants stopped consuming the study beverage; Outcomes and Assessment Methods:; - Weight, height, skinfold thickness (of the biceps, triceps, and subscapular and suprailiac regions), waist circumference, and arm-to-leg electrical impedance were measured by trained researchers.; - At baseline, 6, 12, 18 mo | [underlined: BMI z-score], Mean (SD or 95% CI) Within group: 0mo, 18mo; Sugar: 0.01 (1.04), 0.15 (1.06); Sugar-free: 0.06 (1.00), 0.08 (0.99); Between groups: Δ18mo; −0.13 (−0.21, −0.05), p=0.001; [underlined: Height (cm),] Mean (SD or 95% CI) Within group: 0mo, 18mo; Sugar: 133.02 (12.71), 143.67 (13.05); Sugar-free: 132.06 (12.55), 142.34 (12.48); Between groups: Δ18mo; −0.37 (−0.72, −0.02), p=0.04; [underlined: Height z-score,] Mean (SD) Within group: 0mo, 18mo; Sugar: 0.03 (0.99), 0.09 (0.99); Sugar-free: −0.09 (1.00), −0.07 (0.99); Between groups: Δ18mo; −0.04 (−0.10, 0.02), p=0.17; [underlined: Sum skinfolds (mm),] Mean (SD or 95% CI) Within group: 0mo, 18mo; Sugar: 35.6 (17.9), 41.1 (21.1); Sugar-free: 36.4 (17.7), 39.6 (20.4); Between groups: Δ18mo; −2.2 (−4.0, −0.4), p=0.02; [underlined: Waist-to-height ratio (%),] Mean (SD or 95% CI); Within group: 0mo, 18mo Sugar: 44.2 (4.0), 43.7 (4.0); Sugar-free: 44.6 (4.0), 43.7 (4.0); Between groups: Δ18mo; −0.4 (−1.0, −0.0), p=0.05; [underlined: Fat mass (kg)], Mean (SD or 95% CI) Within group: 0mo, 18mo; Sugar: 5.70 (3.68), 7.28 (4.89); Sugar-free: 5.76 (3.85), 6.77 (4.71); Between groups: Δ18mo; −0.57 (−1.02, −0.12), p=0.02; [underlined: Fat mass (% of body weight),] Mean (SD or 95% CI); Within group: 0mo, 18mo; Sugar: 17.67 (6.92), 18.05 (8.25); Sugar-free: 17.91 (7.01), 17.22 (8.44); Between groups: Δ18mo; −1.07 (−1.99, −0.15), p=0.02; [underlined: WC (cm),] Mean (SD or 95% CI); Within group: 0mo, 18mo; Sugar: 58.69 (7.05), 62.72 (7.92); Sugar-free: 58.85 (7.44), 62.22 (7.97); Between groups: Δ18mo; −0.66 (−1.23, −0.09), p=0.02; [underlined: Weight (kg)], Mean (SD or 95% CI); Within group: 0mo, 18mo; Sugar: 30.33 (8.82), 37.69 (11.05); Sugar-free: 30.04 (8.93), 36.39 (10.41); Between groups: Δ18mo; −1.01 (−1.54, −0.48), p<0.001 | Model Adjustments:; - TEI: no; Limitations:; - Drinks were designed for the study that may not be commercially available; Funding: Netherlands organization for Health Research and Development; Netherlands Heart Foundation; Royal Netherlands Academy of Arts and Sciences
Ebbeling, 2006^23^; RCT-Parallel, Beverages and Student Health (BASH), U.S.; Baseline N=103, Analytic N=103 (Attrition: 0%); Power: Power analysis [80% power with an α=0.05 to detect effect size of 0.51 corresponding with 3.1% mean change in BMI]; Included in meta-analysis: Yes; Participant characteristics at baseline: adolescents; - Age: ~15.9 (1.1)y; - Female: 54%; - Race/ethnicity: White: 36%; Nonwhite: 64%; 17% Hispanic; - SEP: 29% with household income ≥$60,000/yr; 17% resided in subsidized housing; - Anthropometry: BMI ~25 kg/m^2^, 45% with BMI ≥85%tile; - Physical activity: ~1.69 MET level; - Diet quality: NR; - TEI: NR; Energy intake from SSBs: Mean~366 kcal/d; - Study beverage intake at baseline: ≥1 svg/d of SSB (inclusion criterion); Excluded from Study or Analysis: those who reported consuming < 1 svg/d of SSB; living >1 weekend every 2 weeks in a secondary household; currently dieting for purpose of weight loss or taking prescription medications that might affect body weight; those who reported smoking ≥1 cigarette in the past week or were diagnosed as having a major medical illness or eating disorder; those with BMI percen tile<25 | Intervention: Participants were instructed to not buy or drink SSB; noncaloric beverages (diet soft drinks, iced teas, lemonades, and punches) were selected by each household and delivered weekly (4 svgs/d; 360 mL or 12 fl oz per svg) to displace SSB; Comparator: Usual beverage consumption, which was ≥1 svg/d (i.e., 360 mL or 12 fl oz) of SSB (i.e., soft drinks, juice drinks containing <100% juice, punches, lemonades, iced teas, and sports drinks); Study Duration: 25wk; Compliance: Self-reported compliance assessed with questions on adherence to instructions using 10-cm visual analog scale; Outcomes and Assessment Methods:; - Weight and height measured by study staff and used to calculate BMI; - Baseline, 25wk follow-up | [underlined: Change in BMI (kg/m^2^),] Mean (SE), multiple linear regression; Comparator: 0.21 (0.15); Intervention: 0.07 (0.14); Mean Difference: −0.14 (0.21), p=NS; By tertiles of baseline BMI; Upper tertile (BMI ≥25.6 kg/m^2^); Comparator: 0.12 (0.26); Intervention: −0.63 (0.23); Mean Difference: −0.75 (0.34), p=0.03; Middle and lower tertiles; Data NR, p=NS between groups; [underlined: Change in BMI (kg/m^2^)] for every 1 kg/m2 at baseline in intervention group, multiple linear regression; β: −0.081 kg/m2, p=0.0005 | Model Adjustments:; - TEI: no; Limitations:; - No preregistered data analysis plan; Funding:; NIDDK; Charles H. Hood Foundation; NIH
Ebbeling, 2012^22^; RCT-Parallel, U.S.; Baseline N=224, Analytic N=209 (Attrition: 7%); Power: designed to have 80% power at a type I error rate of 5% to detect a net intervention effect with respect to the primary outcome BMI of 0.49, based on pilot; Included in meta-analysis: Yes; Participant characteristics at baseline: adolescents with overweight; - Age: ~15y; - Female: 45%; - Race/ethnicity: 50% White ; 21% Black; 4% Asian; 16% Multiple or other; 19% Hispanic, 71% Non-Hispanic; - SEP: 20% with parental education high school or less; 29% with some college, vocational school, or associate’s degree; 40% with bachelor’s degree or higher; 36% with annual household income ≥$60k, 29% with $30k-$59,999, 24% with >$30k;; - Anthropometry: BMI 30 kg/m^2^; 33% overweight, 56% obesity; - Physical activity: 1.5 (0.18) MET/d; - Diet quality: NR; - TEI: ~1935 kcal/d; - Study beverage intake at baseline: 1.7 svg/d; Excluded from Study or Analysis: not enrolled in grade 9 or 10; BMI <85th percentile for sex and age; reported consuming less than one 12-oz serving of SSB or 100% fruit juice | Intervention: home delivery of noncaloric beverages (e.g., bottled water and “diet” beverages) every 2 weeks, monthly motivational telephone calls with parents (30 minutes per call), and three check-in visits with participants (20 minutes per visit). Written intervention messages with instructions to drink the delivered beverages and not to buy or drink sugar-sweetened beverages were mailed to participants. Unsweetened water was recommended over artificially sweetened beverages. Discussions during telephone calls and check-in visits focused exclusively on beverage consumption, with no attention to other dietary behaviors or to physical activity; n=110; Comparator: mailed $50 supermarket gift cards to participants in the control group at 4 and 8 months as a retention strategy but did not provide instructions on what to purchase with the cards; n=114; Study Duration: 12mo, plus additional 12mo follow-up; Compliance: dietary recall: SSB intake decreased in both groups at 1y and 2y but more so in the intervention group than the control (1y p<0.001; 2y p=0.005); Outcomes and Assessment Methods:; - Weight and height were measured by trained staff and used to calculate BMI. Body fat as a percentage of total body weight was calculated from bioelectrical impedance analysis.; - At baseline, post-intervention (1y), and after follow-up (2y) | [underlined: Change in height (cm),] Mean (SD); Between group differences: 1y, 2y; All participants: −0.2 (0.2), p=0.49; 0.2 (0.4), p=0.67; Non-Hispanic participants: −0.1(0.3), p=0.80; 0.4 (0.4), p=0.29; Hispanic participants: −0.6 (0.6), p=0.30; −1.0 (0.8), p=0.24; Change in body fat % at 1yr, Mean (SE) Between group difference: −0.5 (0.6), p=0.40; [underlined: Change in BMI (kg/m^2^),] Mean (SD); Between group differences: 1y, 2y; All participants: −0.57 (0.28), p=0.045 (Note: when sugar added to model, −0.39, p=0.24); −0.30 (0.40), p=0.46; Non-Hispanic participants: −0.29 (0.31), p=0.36; 0.18 (0.44), p=0.68; Hispanic participants: −1.79 (0.65), p=0.007; −2.35 (0.92), p=0.01; [underlined: Change in weight (kg),] Mean (SD); Between group differences: 1y, 2y; All participants: −1.9 (0.9), p=0.04; −0.8 (1.4), p=0.55; Non-Hispanic participants: −0.8(1.0), p=0.42; 1.1 (1.5), p=0.48; Hispanic participants: −6.4 (2.1), p=0.003; −8.8 (3.1), p=0.005 | Model Adjustments:; - TEI: yes; Limitations:; - Methods for randomization and concealment NR; No preregistered data analysis plan; Funding:; NIDDK; National Center for Research Resources; Harvard Catalyst Clinical and Translational Science Center; New Balance Foundation
Katan, 2016^46^ (see de Ruyter 2012^15^); RCT-Parallel, Kids (DRINK), Netherlands; Baseline N=641, Analytic N=477 (Attrition: 26%); Power: sample size calculation is 212 subjects per treatment, power=0.8;α=0.05; Included in meta-analysis: Yes; Participant characteristics at baseline: children who commonly drank SSBs; - Age: 8.2 (1.8)y; - Female: 47%; - Race/ethnicity: ~78% Dutch ancestry; ~22% Non-Western ancestry; - SEP: Parent education: ~55% college or university degree; ~33% high school diploma; ~14% elementary, vocational; - Anthropometry: Mean BMI ~16.9 kg/m^2^; - Physical activity: NR; - Diet quality: NR; - TEI: NR; - Study beverage intake at baseline: SSBs in classroom at 10am break: 1.02 (0.20); SSB/weekend day: 1.50 (1.40); Excluded from Study or Analysis: did not commonly drink sweetened beverages (<250 mL/d on 3 of 5 school days); <5y at baseline; medication or medical treatment for obesity; diabetes, growth disorders, celiac disease, serious gastroenterologic diseases (e.g., inflammatory bowel disease); medical history or surgery known to interfere with study; participation in another intervention study up to 3 months before and during DRINK if it interfered with study; physical disabilities that interfere with measurements; plans to relocate and change schools; attending a school that was difficult to reach or had few prospective participants; | Intervention: Sugar-containing, non-carbonated beverage; 1 can/d provided (8oz, 250 mL/d), n=322; Note: custom drinks were developed for this study to ensure that the sugar-free and sugar-containing drinks tasted and looked essentially the same; drinks contained 0 or 26 g of sucrose (0 or 104 kcal per day). The sugar-free beverages contained 34 mg of sucralose and 12 mg of acesulfame potassium per can; Comparator: Artificially-sweetened, non-carbonated beverage; 1 can/d provided (8oz, 250 mL/d), n=319; Study Duration: 18mo; Compliance: calculated adherence rate per child during school days from the number of cans returned empty, half-filled, or full during one randomly selected week each month; 26% of participants stopped consuming the study beverage; Outcomes and Assessment Methods:; - Weight, height, skinfold thickness (of the biceps, triceps, and subscapular and suprailiac regions), waist circumference, and arm-to-leg electrical impedance by trained researchers. BMI z score: number of SD by which the BMI differed from the mean for a child’s age and sex in the Netherlands; Lower BMI = below median; Higher BMI = above median. Fat mass: determined by electrical impedance; - Baseline, 6, 12, 18 mo | [underlined: Difference in effect of treatment between children with lower versus higher BMI,] (95% CI); BMI z-score: −0.16 (−0.31, −0.01), P=0.04; Weight (kg): −0.90 (−1.95, 0.14), P=0.09; Height (cm): −0.02 (−0.70, 0.67), P=0.96; Sum skinfolds (mm): −2.94 (−6.16, −0.29), P=0.07; WC (cm): −1.19 (−2.21, −0.16), P=0.02; Fat mass (kg): −0.55 (−1.20, 0.10), P=0.10; Fat mass (%): −0.67 (−2.03, 0.69), P=0.33 | Model Adjustments:; - TEI: no; Limitations:; - Drinks were designed for the study that may not be commercially available; Funding:; Netherlands Organization for Health Research and Development; Netherlands Heart Foundation; Royal Netherlands Academy of Arts and Sciences
Wang, 2022^95^; RCT-Cluster, Nanjing RCT, China; Baseline N=1,686, Analytic N=1,633 (Attrition: 3%); Power: n=690 per group to detect change in the proportion of infrequent (<1 time/wk) consumption of SSB, assuming ≥8% difference in SSBs intake frequency before and after the intervention, power of 90% and alpha of 5%, with a 20% dropout rate of 20%; Included in meta-analysis: Yes; Participant characteristics at baseline: Third graders from rural or urban schools in Nanjing, eastern China; - Age: 9.36 (0.48)y; - Female: 46%; - Race/ethnicity: NR; - SEP: Parental education: 33% ≤9y, 67% >9y; - Anthropometry: Height (cm) Mean (SD): 134.15 (6.60);; Weight (kg) Mean (SD): 31.19 (7.25);; BMI Mean (SD): 17.16 (2.93);; BMI z-score Median (IQR): −0.24(−0.72, 0.58); - Physical activity: Physical activity outside school (min/wk) Mean (SD): 217.33 (221.92); - Diet quality: NR; - TEI: NR; - Study beverage intake at baseline: SSB mL/wk at baseline, Median (IQR): 750 (250, 1750); Excluded from Study or Analysis: students who did not drink any SSBs during the study | Intervention: Students in Intervention schools received school-based and family-based measures to increase knowledge/awareness of SSB, improve the home environment and decrease SSB consumption. Students accepted monthly monitoring along with interventions, for two consecutive semesters. SSB included carbonated beverages, fruit and/or vegetable beverages, sweetened tea beverages, lactobacillus milk beverages, sports and energy beverages, plant-protein beverages, brewed beverages and coffee beverages.; Comparator: Students from Control group schools accepted the regular monitoring, once per semester, without any interventions; Study Duration: 12mo; Compliance: Participants in the intervention group showed greater response to trial’s main goals versus the control group: greater knowledge/awareness of SSB; better family environment with parents and at home; and decreased consumption of total SSB and each category of SSB; Outcomes and Assessment Methods:; - Trained nurses measured children’s heights and weight, which were used to calculate BMI. Age- and sex-adjusted BMI z-scores, derived from the Chinese National Survey on Students Constitution and Health (2014); - At baseline and 12mo follow-up | [underlined: Change in Height (cm),] T-test, Difference (95% CI); All children (n=1633): 0.97 (0.67, 1.26), p<0.001; Parental education ≤9y (n=542): 1.14 (0.60, 1.68), p<0.001; Parental education >9y (n=1091): 0.87 (0.52, 1.22), p<0.001; [underlined: Change in Weight (kg),] T-test, Difference (95% CI); All children (n=1633): −0.13 (−0.43, 0.16), p=0.361; Parental education ≤9y (n=542): −0.02 (−0.54, 0.49), p=0.928; Parental education >9y (n=1091): −0.19 (−0.54, 0.16), p=0.290; [underlined: Change in BMI z-score,] Mann-Whitney test, Difference (95% CI); All children (n=1633): −0.08 (−0.12, −0.04), p<0.001; Parental education ≤9y (n=542): −0.06 (−0.14, −0.01), p=0.103; Parental education >9y (n=1091): −0.09 (−0.14, −0.03), p<0.001; [underlined: Change in BMI z-score by SSB intake change over 12mo,] Median (IQR) change, p-value for difference; Level-Up: Control (CN, n=346): 0.15 (−0.07, 0.42); Intervention (Int, n=273): 0.10 (−.015, 0.41), p = 0.178; Level-Same: CN (n=56): 0.17 (−0.10, 0.52); Int (n=125): 0.04 (−0.24, 0.30), p = 0.044; Level-Down: CN (n=344): 0.14 (−0.08, 0.40), Int (n=489): 0.03 (−0.18, 0.33), p=0.001; [underlined: Change in BMI,] T-test, Difference (95% CI); All children (n=1633): −0.26 (−0.38, −0.12), p<0.001; Parental education ≤9y (n=542): −0.23 (−0.46, 0.00), p=0.053; Parental education >9y (n=1091): −0.26 (−0.42, −0.11), p=0.001 | Model Adjustments:; - TEI: no; Limitations:; - Participants were aware of the intervention; SSB intake self-reported; No pre-specified analysis plan; Method of randomization unclear; Funding:; Jiangsu Provincial Health Commission; Nanjing Municipal Health Commission
CHILDREN AND ADOLESCENTS, COHORT STUDIES
Altman, 2015^1^; PCS, Secondary analysis of RCT, U.S. Analytic N=167; Included in meta-analysis: No; Participant characteristics at baseline: Children and adolescents with overweight and obesity; - Age: 9.4 (1.2)y; - Female: 61%; - Race/ethnicity: White: 63% ; Black: 17%; Other: 17%; Hispanic: 17%; - SEP: Barratt Simplified Measure of Social Status: 43.8 (10.4); Range: 10-65; - Anthropometry: BMI z-score ~2.16; Body fat: ~45%; - Physical activity: moderate-vigorous, ~47min; - Diet quality: baseline HEI mean + SD: 59.3+8.8, 40.6-90.0; - TEI: NR; - Study beverage intake at baseline: NR; Excluded from Study or Analysis: BMI ≤ 85th percentile for age and sex; <7y or >11y; no parent with BMI >25; either the parent or child had an eating disorder, drug or alcohol dependence, or other mental illness diagnosis; low English comprehension; a physical illness or disability that prohibited following dietary recommendations or engaging in moderate to vigorous physical activity, or a medication that could affect weight. | Exposure: Family-based multi-component, behavioral weight-loss intervention that targets both dietary and physical activity modifications. Participants are encouraged to follow a low-energy-density diet by decreasing consumption of high-energy-dense and low-nutrient foods and increasing consumption of low-energy-dense and high nutrient foods; encouraged to decrease consumption of food away from home; Comparator: Change in SSB intake, (continuous; svg/d); Exposure Assessment Methods and Timing:; 3d-24hr recalls completed by parent with assistance from child if present (administered by registered dietitian ) Baseline and 16 wk follow-up; Outcomes and Assessment Methods:; - Body fat (%) assessed via DXA.; - At baseline, 16wk | [underlined: Change in % Body Fat by change in SSB intake (svg/d)] (n=167), linear regression Beta: 1.113; β: 0.241, p=0.122 | Model Adjustments:; - TEI: yes; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position, anthropometry at baseline, physical activity; - Other: Study site; Limitations:; - Did not account for key confounders: diet quality; - High attrition/missing data with no information on non-completers; No preregistered data analysis plan; Funding:; NIH
Alviso-Orellana, 2018^2^; PCS, Young Lives cohort study, Peru; Analytic N=1,813; Included in meta-analysis: Yes; Participant characteristics at baseline: Children with normal weight and high risk of overweight; - Age: ~8y; - Female: 49%; - Race/ethnicity: NR; - SEP: NR; - Anthropometry: 22% with overweight; WC=~61cm; - Physical activity: none=9%; daily=33%; - Diet quality: Snack consumption: never = 18.5%; 2-6/week=48%, Daily= 3.6%; - TEI: NR; - Study beverage intake at baseline: never=13%, daily=3%; Excluded from Study or Analysis: Age <7y or >8y in third round of data collection; incomplete data in the variables of interest | Exposure: Includes: fizzy, sweet soft drinks such as sodas. Authors noted that “question used to assess sweetened beverage consumption was not specific to sodas, but potentially included diet sodas, sports drinks, etc.; Comparator: SSB intake, categorical: Never (ref), Up to every 2 wk, 2-6 times/wk, Daily; Exposure Assessment Methods and Timing:; Maternal report questionnaire; representing intake over last 30d Baseline; Outcomes and Assessment Methods:; - Overweight based on BMI and the IOTF sex- and age- pecific BMI cut-off points were used ; Waist and abdominal circumference (methods NR); - At baseline, 4y follow-up | [underlined: WC,] cm, β (95% CI); Never (ref); Up to every 2 wk: 0.16 (−0.64, 0.96); 2-6 times/wk: 0.80 (−0.01, 1.61); Daily: 1.43 (−0.41, 3.27); [underlined: Incidence of overweight] (n=1414), RR (95% CI); Never (ref); Up to every 2 wk: 1.15 (0.66, 1.99); times/wk: 1.34 (0.80, 2.25); Daily: 2.12 (1.05, 4.28), P<0.05; [underlined: Weight,] kg, β (95% CI); Never (ref); Up to every 2 wk: 0.58 (−0.22, 1.37); 2-6 times/wk: 0.55 (−0.21, 1.32); Daily: 2.29 (0.62, 3.96), P<0.05; [underlined: BMI], kg/m2, β (95% CI); Never (ref); Up to every 2 wk: −0.08 (−0.39, 0.24); 2-6 times/wk: 0.14 (−0.15, 0.43); Daily: 0.74 (0.15, 1.33), P<0.05 | Model Adjustments:; - TEI: no; - Key confounders: sex, age, socioeconomic position (wealth index built using household assets and facilities),physical activity; - Other: mother’s BMI at baseline; Limitations:; - Did not account for key confounders: race and/or ethnicity, anthropometry at baseline, diet quality; - Exposure assessment tool not validated; Exposure data only measured at baseline; No preregistered data analysis plan; Exposure is frequency of SSB intake, does not account for amount of intake;; Outcome assessment methods NR; Peru is considered high HDI as of 2005; however this study excluded wealthiest areas and oversampled poor areas (generalizability); Funding:; Wellcome Trust Research Training Fellowship in Public Health and Tropical Medicine
Ambrosini, 2013^4^; PCS, Western Australian Pregnancy Cohort (Raine), Australia; Analytic N=1,009; Included in meta-analysis: Yes; Participant characteristics at baseline: adolescents; - Age: 14y; - Female: 48%; - Race/ethnicity: NR; - SEP: NR; - Anthropometry: BMI ~21.3; WC: ~75cm; - Physical activity: Physical fitness~110 watts (measured by using the Physical Working; Capacity 170 test on a bicycle ergometer); tertile 1=-0.43+0.67; tertile 2=-0.03+0.78; tertile 3= 0.47+0.9; Healthy dietary pattern z-score mean (SD) by tertile of SSB:; tertile 1 = 0.2 +0.9; tertile 2= 0.04+0.9; tertile 3= −0.24 +0.8; Tertile 1: 48 (37); Tertile 2: 224 (58); Tertile 3: 651 (321); - Diet quality:; Western dietary pattern z-score by tertile of SSB:; - TEI: ~9.7 MJ (~2318 kcal); - Study beverage intake at baseline: SSB g/d, Mean (SD); Excluded from Study or Analysis: Not fasting before venepuncture | Exposure: carbonated (soft) drinks, cordials or squash (fruit drink concentrate), and fruit juice drinks (with the exclusion of 100% juice) (1 svg= 1 cup = 250mL = 261g); Comparator: SSB intake (categorical, svg/d), Tertiles; Tertile 1: 0–0.5 svg/d (0–130 g/d); Tertile 2: 0.5–1.3 svg/d (130–329 g/d); Tertile 3: >1.3 svg/d (331–2876 g/d); Exposure Assessment Methods and Timing: Validated semi-quantitative FFQ, included frequency of consumption and portion sizes; represents usual dietary intake over the previous year (at 14y, parents assisted); Baseline (14y), 3y follow-up (17y); Outcomes and Assessment Methods:; - Height and weight: calibrated easurements made using electronic chair scales and a stadiometer ; Overweight and obesity defined using International Obesity Task Force cutoffs for BMI; Waist circumference (WC) measured at the level of the umbilicus to the nearest 0.1 cm, and the average of 2 measurements was used; - Baseline, 3y follow-up (17yo) | [underlined: WC, % of change] (95%CI); Girls (n=656): Tertile 1: (ref); Tertile 2: 0.8 (−0.1, 1.7), P=0.08; Tertile 3: 0.9 (−0.2, 2.0), P=0.09; P-trend: 0.07; Boys (n=704): Tertile 1: (ref); Tertile 2: 1.3 (0.3, 2.2), P=0.011; Tertile 3: 1.4 (0.2, 2.3), P=0.019; P-trend: 0.025; [underlined: BMI, % of change] (95%CI); Girls (n=660):; Tertile 1: (ref); Tertile 2: 0.4 (−1.3, 2.1), P=0.64; Tertile 3: 3.6 (1.5, 5.8), P=0.001; P-trend: 0.002; Boys (n=706):; Tertile 1: (ref); Tertile 2: 0.3 (−1.6, 2.3), P=0.75; Tertile 3: 0.8 (−1.3, 2.9), P=0.46; P-trend: 0.46; [underlined: Odds of overweight or obesity,] OR (95%CI); Girls (n=624):; Tertile 1: (ref); Tertile 2: 1.1 (0.5, 2.5), P=0.75; Tertile 3: 3.8 (1.5, 9.3), P=0.004; P-trend: 0.005; Boys (n=680):; Tertile 1: (ref); Tertile 2: 1.5 (0.6, 3.3), P=0.37; Tertile 3: 0.8 (0.3, 2.1), P=0.76; P-trend: 0.72 | Model Adjustments:; - TEI: yes and no; - Key confounders: sex, age, SEP (maternal education, family income), anthropometry at baseline, physical activity, diet quality (Western dietary pattern scores); - Other: dietary misreporting, pubertal development; Limitations:; - Did not account for key confounders: race and/or ethnicity,; - High attrition/missing data, no information on non-completers; No preregistered data analysis plan; Funding:; National Heart Foundation of Australia and Beyond Blue Cardiovascular Disease and Depression Strategic Research Program; Australian National Health and Medical Research Council; UK Medical Research Council
Arenaza, 2020^5^; PCS, Secondary analysis of EFIGRO NRCT, Spain; Analytic N=81; Included in meta-analysis: No; Participant characteristics at baseline: children with overweight or obesity; - Age: 10.6 (1.1)y; - Female: 53%; - Race/ethnicity: 90% with Spanish-origin mother; - SEP: 74% high educational level of mother (“high” not defined); - Anthropometry: BMI ~25 (3) kg/m^2^; 56% with obesity; Fat mass index: ~10.1 kg/m2; - Physical activity: NR; - Diet quality: ~1.7 HDI score (range 0-7); - TEI: ~1840 kcal/d; - Study beverage intake at baseline: ~75 g/d SSB; Excluded from Study or Analysis: did not complete study or attend at least 50% of lifestyle education sessions; missing 24-h recalls at baseline and post-intervention | Exposure: SSB; Comparator: Continuous intake (g/d); Exposure Assessment Methods and Timing:; Two 24hr recalls; average intake was calculated; At baseline, 22wk; Outcomes and Assessment Methods:; - Fat mass and abdominal fat measured using DEXA.; - At baseline, 22wk | [underlined: Change in fat mass index (kg/m2) by change in SSB intake (g/d) over 22wk]; All participants: r=-0.017 p=0.897; Control group: r=-0.058, p=0.726; Exercise group: r=0.010, p=0.968; [underlined: Change in abdominal fat (kg) by change in SSB intake (g/d) over 22wk]; All participants: r=-0.083, p=0.516; Control group: r=-0.021, p=0.899; Exercise group: r=-0.351, p=0.129 | Model Adjustments:; - TEI: yes; - Key confounders: sex, age, anthropometry at baseline; - Other: intervention group; Limitations:; - Did not account for key confounders: race and/or ethnicity, socioeconomic position, physical activity, diet quality; - No information on non-completers; Funding:; Spanish Ministry of Industry and Competitiveness; European Regional Development Funds; University of the Basque Country, Government of the Basque Country, Junta de Andalucia, Consejeria de Conocimiento, Investigacion y Universidades, EDRF
Bennett, 2022^6^; PCS, GEN2 Raine Study, Australia; Analytic N=958; Included in meta-analysis: No; Participant characteristics at baseline: adolescents and young adults; - Age: ~14y; - Female: 49%; - Race/ethnicity: NR; - SEP: Maternal education >12 years: 48%; - Anthropometry: BMI, mean (SD): 20.9 (3.5)y; - Physical activity: NR at baseline Physical activity level at 20y: 46% high; 43% moderate; 11% low; - Diet quality: Healthy dietary pattern z-score at 14y (n=958): 0.0 (0.9); Western dietary pattern z-score at 14y (n=958): −0.1 (0.8); Dietary patterns derived from factor analysis of food intake at each follow-up.; - TEI: NR at baseline; mean (SD): 1944 (1074) kcal/d at 20y; - Study beverage intake at baseline: median (IQR) at 14y, n=958: 207 (63, 390) mL/d; Excluded from Study or Analysis: no valid DXA at 20y; no measured SSB intake at 14 or 17y | Exposure: cola, other carbonated SSB (i.e., fizzy drinks other than cola, including mineral water with juice), cordials, fruit drinks with ≤35% fruit juice; Comparator: Categorical intake: <0.5 svg/d, 0.5-1.3 svg/d, >1.3 svg/d; Exposure Assessment Methods and Timing: Validated semiquantitative FFQ used to estimate energy/nutrient intake over past 12mo. Questions were asked on the frequency and size (cup, glass, can, bottle, carton) of SSB.; SSB intake (mL/d) calculated from frequency and serving size (250 mL = 1 serving). SSB intake at each age categorized into 3 groups using tertile cutoffs at 14y: low intake: 0-0.5 svg/d; medium intake: >0.5-1.3 svg/d; high intake: >1.3 svg/d; 14y, 17y; Outcomes and Assessment Methods:; - Total body fat, lean mass measured by DXA; - 20y | [underlined: Total body fat mass (kg) at 20y by SSB intake at 14y,] adjusted mean (SE), general linear models; Males (n=499); <0.5 svg/d: 17.1 (0.7); 0.5-1.3 svg/d: 17.5 (0.7); >1.3 svg/d: 17.1 (0.7); P=NS; Females (n=459); <0.5 svg/d: 26.6 (0.7); 0.5-1.3 svg/d: 26.1 (0.8); >1.3 svg/d: 27.1 (0.9); P=NS; [underlined: Total body fat mass (kg) at 20y by SSB intake at 17y,] adjusted mean (SE), general linear models; Males (n=322); <0.5 svg/d: 16.3 (0.9); 0.5-1.3 svg/d: 18.1 (1.0); >1.3 svg/d: 17.4 (0.8); P=NS; Females (n=367); <0.5 svg/d: 25.7 (0.8); 0.5-1.3 svg/d: 27.4 (1.0); >1.3 svg/d: 28.0 (1.2); P=NS; [underlined: Total body lean mass (kg) at 20y by SSB intake at 14y,] adjusted mean (SE), general linear models; Males (n=493); <0.5 svg/d: 57.3 (0.5); 0.5-1.3 svg/d: 57.2 (0.5); >1.3 svg/d: 56.4 (0.5); P=NS; Females (N=459); <0.5 svg/d: 36.5 (0.3); 0.5-1.3 svg/d: 36.2 (0.3); >1.3 svg/d: 37.1 (0.4); P=NS; [underlined: Total body lean mass (kg) at 20y by SSB intake at 17y,] adjusted mean (SE), general linear models; Males (n=322); <0.5 svg/d: 56.8 (0.6); 0.5-1.3 svg/d: 56.9 (0.6); >1.3 svg/d: 56.8 (0.6); P=NS; Females (N=367); <0.5 svg/d: 36.5 (0.3); 0.5-1.3 svg/d: 36.5 (0.4); >1.3 svg/d: 37.4 (0.5); P=NS | Model Adjustments:; - TEI: yes; - Key confounders: sex, age, socioeconomic position (maternal education), physical activity at 20y, diet quality at 20y; - Other: maternal BMI, screen time at 20y, dietary misreporting, height; Limitations:; - Did not account for key confounders: race and/or ethnicity, anthropometry at baseline; - Unclear if sufficiently powered for sex-stratified analyses; High attrition with no information on non-completers; No preregistered data analysis plan; Funding:; National Health and Medical Research Council (NHMRC) of Australia
Berkey, 2004^7^; PCS, Growing Up Today Study (GUTS), U.S.; Analytic N=11,634; Included in meta-analysis: Yes; Participant characteristics at baseline: children and adolescents; - Age: NR; - Female: 57%; - Race/ethnicity: White: 95%; - SEP: NR; - Anthropometry: Overweight (>85th percentile CDC BMI charts): boys: 23.2%; girls: 17.5%;; Very lean (<10th percentile): boys: 7.2%; girls: 8.6%; - Physical activity: NR; - Diet quality: NR; - TEI: Boys, Mean~2290 kcal/d; Girls, Mean~2050 kcal/d; - Study beverage intake at baseline: Boys: Range: 0.34-0.77 svg/d; Girls: Range: 0.27-0.50 svg/d; Excluded from Study or Analysis: age < 9y or >14y at baseline (1996); any height >3 SD beyond gender-age-specific mean height (0.46% excluded); any 1-y height change which declined by >1 inch or increased by >3 SD above mean change (1.65% excluded); BMI < 12.0 kg/m2; BMI >3 SD above or below gender-age-specific mean (0.87% excluded); | Exposure: Soda, sweetened iced tea, noncarbonated fruit drinks; Comparator: SSB intake (continuous); Exposure Assessment Methods and Timing:; Self-administered semi-quantitative, validated FFQ for older children and adolescents; Represents intake during previous year; At baseline, 1y follow-up, 2y follow-up; Outcomes and Assessment Methods:; - BMI from height and weight self-reported by children with measuring instructions and suggestion to ask someone for help provided (all have mothers who are nurses in NHSII); - At baseline, 1y, & 2y follow-ups | [underlined: BMI change over 1y by 1 svg/d increase in soda intake, kg/m^2^,] β (SE), Linear regression Not adjusted for TEI; Boys: 0.040 (0.016), P=0.012; Girls: 0.026 (0.015), P=0.082; Adjusted for TEI; Boys: 0.024 (0.018), P=0.178; Girls: 0.023 (0.016), P=0.159; [underlined: BMI change over 1y per daily serving of soda], kg/m^2^, β (SE), Linear regression Not adjusted for TEI; Boys: 0.028 (0.014), P=0.056; Girls: 0.021 (0.012), P=0.096; Adjusted for TEI; Boys: 0.015 (0.015), P=0.317; Girls: 0.019 (0.014), P=0.167 | Model Adjustments:; - TEI: yes and no; - Key confounders: Sex, age, race and/or ethnicity, anthropometry at baseline, physical activity; - Other: Tanner stage, menarche (girls), height growth, milk type (whole/2%/1%/nonfat/soy), inactivity, other beverage intake (sugar added, diet soda, fruit juices); Limitations:; - Did not account for key confounders: SEP, diet quality; - Differences in attrition (children lost to follow-up were older and had higher sugar added beverage intake and lower milk intake at baseline); self-reported outcome data; no preregistered data analysis plan; Funding:; NIH; Boston Obesity Nutrition Research Center Grant; CDC; Economic Research Service of the USDA; Kellogg’s
Bigornia, 2015^8^; PCS, Avon Longitudinal Study of Parents and Children (ALSPAC), UK; Analytic N=2,455; Included in meta-analysis: No; Participant characteristics at baseline: Children; - Age: ~10.6y; - Female: 53%; - Race/ethnicity: NR; - SEP: mothers, college degree or higher: ~50%; - Anthropometry: BMI ~17.5; ~21% with overweight/obesity; WC: ~63cm; - Physical activity:; - Diet quality: Fruit and vegetable intake (g/d): mean (IQR); boys- 117.5 (127); girls- 125 (121.7); - TEI: ~1900 kcal/d; - Study beverage intake at baseline: ~60% consumers at baseline; ~0.35 svg/d; Excluded from Study or Analysis: missing anthropometric, DXA, dietary, and/or physical activity data | Exposure: full-sugar fruit squashes, cordials and fizzy drinks (i.e. soda) with added sugar; Not including reduced-sugar or artificially sweetened beverages; 1 svg=180g; Comparator: SSB, continuous; Exposure Assessment Methods and Timing: 3d dietary record completed by children with parental assistance, reviewed by fieldworker; At ages 10, 13y; Outcomes and Assessment Methods:; - Weight measured using Tanita body fat analyser. Height measured using a Harpenden stadiometer. BMI was calculated as kg/m2. With overweight/obesity: BMI≥25 kg/m2 based on International Obesity Task Force age- and sex-specific categories.; Waist circumference (WC) measured at the midpoint between the lowest rib and the top of the iliac crest. Total body fat mass (TBFM) measured with DXA using a Lunar Prodigy narrow fan beam densitometer; - At ages 10, 11, 13y | [underlined: Change of SSB intake from ages 10-13y on adiposity outcomes at 13y] (n=1059), β; WC (cm):; Unadj TEI: 0.097, P<0.001; Adj TEI: attenuated by 22%, Data NR; Total body fat mass (kg):; Unadj TEI: 0.065, P=0.003; Adj TEI: remained similar, Data NR; [underlined: Change of SSB intake from ages 10-13y on WC at 13y,] adjusting for adiposity, β; WC, adjusting for BMI: 0.042, P=0.02; WC, adjusting for TBFM: 0.048, P=0.01; [underlined: Change of SSB intake from ages 10-13y on adiposity outcomes at 13y] (n=1059), β; Weight (kg):; Unadj TEI: 0.066, P=0.001;; Adj TEI: attenuated by 47%, Data NR; BMI (kg/m2):; Unadj TEI: 0.074, P<0.001; Adj TEI: attenuated by 25%, Data NR | Model Adjustments:; - TEI: yes and no; - Key confounders: sex, age, socioeconomic position (maternal education), anthropometry at baseline, physical activity, diet quality (fruit and vegetable intake, total fat intake from 10-13 years); - Other:; Limitations:; - Did not account for key confounders: race and/or ethnicity; - Exposure data collection tool not validated, No preregistered data analysis plan; Funding:; UK Medical Research Council; Welcome Trust; University of Bristol; American Diabetes Association
Blum, 2005^9^; PCS, U.S.; Analytic N=166; Included in meta-analysis: No; Participant characteristics at baseline: Children; - Age: 9.3 (1.0)y; - Female: 55%; - Race/ethnicity: White: 94%; - SEP: NR; - Anthropometry: BMI z-score, Mean=0.47, SD=1.0;; Height, Mean=139.4 cm, SD=7.9; Weight, Mean=35.7 kg, SD=8.1; - Physical activity: NR; - Diet quality: NR; - TEI: Mean=1957.7 kcal/d, SD=575.3; - Study beverage intake at baseline: Mean (SD): 7.4 (9.3) oz/d; Excluded from Study or Analysis: not in grades 3-6, missing data; outlier values (>2.5 SD) on change in BMIz (n=2) | Exposure: Regular soda, Hi-C, sports drinks, kool-ade, fruit flavored drinks, ice tea, hot chocolate; Comparator: SSB intake (continuous, oz/d); Exposure Assessment Methods and Timing: 24-hr recall with two interviews per 24-hr period; parents of random sub-sample called to verify consumption at home; Represents intake during past 24-hr on a school day; Baseline, 2y; Outcomes and Assessment Methods:; - Weight and height measured by study staff; BMI z-score calculated (CDC age and gender specific) from height and weight; Overweight: BMI z-score ≥1.0; Normal weight: BMI z-score<1.0; - Baseline, 2y | [underlined: BMI z-score,] linear regression; Increase per oz/d increase in baseline intake: P=NS, Data: NR; [underlined: Change in soda intake for Change-in-BMI z-score subgroups], oz/d; ANOVA, Mean (SD): Unadjusted analysis; Within group differences (t-tests):; Normal weight at baseline & 2y, n=99: 0.7 (14.0), P=NS; Overweight at baseline & 2y, n=48; 1.5 (13.3), P=NS; Gained weight (Normal weight at baseline; Overweight at 2y), n=11: −1.3 (6.8), P=NS; Lost weight (Overweight at baseline; Normal weight at 2y), n=6: 0.0 (10.7), P=NS Between group differences (ANOVA): All NS | Model Adjustments:; - TEI: yes; - Key confounders: Sex, age, anthropometry at baseline; - Other: Baseline beverage intake; Limitations:; - Did not account for key confounders: Race and/or ethnicity, SEP, physical activity, diet quality; - Single 24-hr recall used to assess intake; impact of high level of missing data on analyses unclear; no preregistered analysis plan; Funding:; NR
Cantoral, 2016^10^; PCS, Early Life Exposure in Mexico to Environmental Toxicants (ELEMENT) project & Formative Children’s Environmental Health (CEH) Centre, Mexico, Mexico; Analytic N=227; Included in meta-analysis: Yes; Participant characteristics at baseline: Children (8-14y); - Age: NR; - Female: 54%; - Race/ethnicity: NR; - SEP: 94% monthly family income level <$35000 Mexican pesos (~$2333 USD); - Anthropometry: 22% with obesity, 19% Waist circumference >90th%; - Physical activity: 5.8 (3.3) hr/wk; - Diet quality: NR; - TEI: 2637 (844) kcal/d; - Study beverage intake at baseline: mL/d, Mean (SD); SSB intake at revisit stage: 421 (352) 73% introduced to SSBs <12mo of age; Excluded from Study or Analysis: Age < 8y or >14y; missing data | Exposure: SSBs (sodas, commercial fruit drinks and flavored water with sugar; not including natural fruit or vegetable juices); Comparator: Categorical intake; Initiation of SSBs: ≤12mo, >12mo (ref); Cumulative consumption of SSBs, ages 1-5y: tertiles; T1: 1642–15,242 mL; T2: 15,410–22,484 mL; T3: 22,731–55,913 mL; Exposure Assessment Methods and Timing:; Validated semi-quantitative FFQ; estimates intake over previous 3mo; At baseline (age 12mo), every 6mo, and at “revisit” stage (age 8-14y); Outcomes and Assessment Methods:; - Weight measured by trained personnel with a Bame scale, Height measured by trained personnel with a stadiometer, Waist circumference measured by trained personnel using a measuring tape, ‘With obesity’: >2 SD of BMI z-score, according to WHO,; Abdominal obesity: Waist circumference ≥ 90th percentile for age and sex; - At revisit stage (age 8-14y) | [underlined: Odds of Abdominal obesity (WC>90%) at age 8-14y by SSB intake from age 1-5y], OR (95% CI); By age of introduction of SSB: >12 mo: ref; ≤12mo: 1.70 (0.70, 4.09); By cumulative SSB intake (1-5y):; T1: ref; T2: 1.14 (0.42, 3.07); T3: 2.70 (1.03, 7.03); P-trend: 0.03; [underlined: Odds of Obesity (>2SD BMI z-score) at age 8-14y by SSB intake from age 1-5y], OR (95% CI); By age of introduction of SSB: >12 mo: ref; ≤12mo: 2.00 (0.87, 4.59); By cumulative SSB intake (1-5y):; T1: ref; T2: 0.84 (0.32, 2.13); T3: 2.99 (1.27, 7.00); P-trend=0.01 | Model Adjustments:; - TEI: yes; - Key confounders: sex, age, physical activity; - Other: timing, temporal use, medications, supplements, alcohol; Limitations:; - Did not account for key confounders: race and/or ethnicity, diet quality, diet quality, anthropometry at baseline, socioeconomic position; - Follow-up time may differ among participants, No preregistered data analysis plan; Funding:; US NIEHS; Consejo Nacional de Ciencia y Tecnologıa (CONACyT); NIEHS/US EPA Formative Children’s Center for Environmental Health and Disease Prevention Research
Carlson, 2012^11^; PCS, MOVE Project (RCT), U.S.; Analytic N=254; Included in meta-analysis: Yes; Participant characteristics at baseline: Children; - Age: 6.7 (0.7)y; - Female: 56%; - Race/ethnicity: 39% non-Hispanic white; 48% Latino; - SEP: Parent with college degree: 41%; - Anthropometry: BMI: ≥85th% 20%, ≥95th% 15%; Body Fat %, Mean (SD)=29.9 (8.7); - Physical activity: 4.35 (2.00) days/wk; - Diet quality: Mean (SD); High fat foods: 3.49 (1.66) foods/d; Fruits and vegetables: 3.9 (1.68) servings/d; Fast food/restaurants: 1.67 (1.16) times/wk Meals in front of TV: 1.72 (2.06) times/wk Breakfast as a family: 3.02 (2.08) days/wk Dinner as a family: 5.10 (1.53) days/wk; - TEI: NR; - Study beverage intake at baseline: Mean (SD): 0.54 (0.59) servings/d; Excluded from Study or Analysis: not in control group of MOVE Project; age <6y or >7y at baseline; living in a foster or group home; having a medical and/or psychological condition that affected diet, physical activity, growth, or weight; being unable to speak, read, and understand either English or Spanish; lost to follow-up (n=14); change in % body fat by ≥5 SD from the mean change (n=3) | Exposure: soda (svg=12 oz); Hawaiian punch, fruit drinks, lemonade, sugar-sweetened ice tea, Tampico, other noncarbonated sugary drinks (svg=8 oz); sports drinks like Gatorade or Powerade (svg=12oz); Comparator: SSB intake (continuous; svg/d); Exposure Assessment Methods and Timing:; Unvalidated survey completed by parents; represents usual dietary behavior; Baseline, 2y; Outcomes and Assessment Methods:; - Height and weight measured by trained staff. Age- and gender-specific BMI percentiles and z-scores (BMI z-score) calculated using CDC growth charts. Percent body fat measured using bioelectrical impedance analysis and Schaefer equation; - Baseline, 2y | [underlined: BMI z-score], Linear regression, β (95% CI); Change per svg/d increase:; 0.11 (−0.03, 0.25), P=0.124; [underlined: Percent Body Fat], Linear regression, β (95% CI); Change per svg/d increase:; 1.40 (0.09, 2.72), P=0.036 | Model Adjustments:; - TEI: no; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position (parent education); - Other: Baseline height; Limitations:; - Did not account for key confounders: anthropometry at baseline, physical activity, diet quality; - Exposure assessment tool not validated; No preregistered data analysis plan; Funding:; NIDDK
Chen, 2019^13^; PCS, Secondary analysis of the “iStart Smart for Teens” RCT, U.S.; Analytic N=21 (intervention group); Included in meta-analysis: Yes; Participant characteristics at baseline: adolescents; - Age: 14.9 (1.67)y; - Female: 43%; - Race/ethnicity: 100% Chinese American; - SEP: 95% annual family income <$40k; - Anthropometry: BMI, mean (SD): 27.37 (3.26) kg/m^2^; all with BMI ≥85th percentile; - Physical activity: Mean (SD): 2.36 (0.99) d/wk of being active >60 min; - Diet quality: Vegetable and fruit intake, mean (SD): 1.43 (.90) svg/d; Fast food intake, mean (SD): 2.39 (0.39) times/wk; - TEI: NR; - Study beverage intake at baseline: Mean (SD): 5.33 (2.46) svg/d; Excluded from Study or Analysis: did not self-identify as Chinese American; <13 or >18y; BMI <85th percentile; did not own a smartphone, did not have access to a computer with internet access; unable to speak and read English; unable to engage in activities of daily living such as attending school; not a patient at one of the clinics in the study | Exposure: Soft drinks (soda and sugar-sweetened drinks); Comparator: Continuous intake (svg/d), change in SSB consumption; Exposure Assessment Methods and Timing: 2 questions on SSB consumption, including “Yesterday, how many glasses or cans of sweetened fruit drinks, sports drink, or energy drinks, did you drink?” At baseline, 6mo follow-up; Outcomes and Assessment Methods:; - Height and weight were measured and used to calculate BMI. Overweight defined as BMI percentile between 85th-95thpercentile; obesity defined as BMI %tile >95th percentile; - At baseline, 6mo follow-up | [underlined: Change in BMIz by change in SSB consumption over 6mo], univariate regression Intervention group: β = −0.08, sr2: 0.16, F=7.51, p=0.015; [underlined: Change in BMI by change in SSB consumption over 6mo], β, univariate regression; Intervention group: Data NR, p=NS | Model Adjustments:; - TEI: no; - Key confounders: sex, age, race and/or ethnicity, anthropometry at baseline; - Other: intervention group; Limitations:; - Did not account for key confounders: socioeconomic position, physical activity, diet quality; - No information on control group participants; Funding:; American Nurses Foundation Research Award, NIH (via University of California-San Francisco Clinical and Translational Science Institute)
DeBoer, 2013^16^; PCS, Early Childhood Longitudinal Survey—Birth cohort (ECLS-B), U.S. Analytic N=6,800; Included in meta-analysis: No; Participant characteristics at baseline: children; - Age: 2y; - Female: 49%; - Race/ethnicity: 43% White; 15% Black; 10% Asian; 21% Hispanic; - SEP: 18% Lowest SES quintile based on family income, and maternal/paternal education and occupation; - Anthropometry: 91% Normal weight; - Physical activity: NR; - Diet quality: NR; - TEI: NR; - Study beverage intake at baseline: 9% drank ≤1 svg/d of SSB at 2y; Excluded from Study or Analysis: children <24mo at the 2y time point; missing data | Exposure: SSB intake (soda pop, for example, Coke, Pepsi, or Mountain Dew; sports drinks, for example, Gatorade; fruit drinks that are not 100% fruit juice, for example, Kool-Aid, Sunny Delight, Hi-C, Fruitopia, or Fruitworks); 8-oz svg=1 glass; Comparator: Dichotomous intake (<1 svg/d versus ≥1 svg/d); Exposure Assessment Methods and Timing:; Primary caregiver completed a computer-assisted interview. At 2y visit, parents were asked whether their child usually drinks SSB with meals and snacks. If the parent answered yes to SSB consumption at either meals or snacks, the child was categorized as an SSB regular drinker; if parent answered no to SSB consumption at meals/snacks, the child was categorized as a SSB infrequent/nondrinker. At 4y visit, parents were asked how many times their child drank SSB. Categories of consumption (in 8-ounce servings) included no intake during past 7 days, 1-3 times during past 7 days, 4-6 times during past 7 days, once daily, twice daily, 3 times daily, ≥4 times daily. For all analyses at 2y and for dichotomous analyses at 4 and 5y, children drinking ≥1 svg/d of SSB were categorized as regular drinkers and those drinking <1 svg/d were categorized as infrequent/nondrinkers.; At 2, 4, and 5y; Outcomes and Assessment Methods:; - Height and weight were measured and used to calculate BMI and age- and gender-specific BMI z-scores (BMIz) based on 2000 CDC growth charts; - At 2, 4, and 5y | [underlined: Change in BMIz], Linear regression; From 2-4y based on SSB at 2y; <1 svg/d: REF; ≥1 svg/d: greater increase in BMIz (Data NR), p<0.05; From 4-5y based on SSB at 4y; <1 svg/d: REF; ≥1 svg/d: similar change in BMIz (Data NR), p=NS | Model Adjustments:; - TEI: no; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position, anthropometry at baseline; - Other: none; Limitations:; - Did not account for key confounders: physical activity, diet quality; - Exposure assessment tool not validated; No information on non-completers; No preregistered data analysis plan; Funding:; NIH
De Coen, 2014^14^; PCS, POP-project (Prevention of Overweight among Pre-school and school children), Belgium; Analytic N=473; Included in meta-analysis: Yes; Participant characteristics at baseline: children; - Age: 4.95 (1.29)y; - Female: 53%; - Race/ethnicity: 94% spoke Dutch at home; - SEP: Majority of parents in paid work (86% mothers, 91% fathers); - Anthropometry: 19% Overweight; - Physical activity: At home 5.98 (2.60) hr/wk, Structured 4.06 (4.72) hr/wk; - Diet quality: 136 g/d fruit, 72 g/d vegetables; - TEI: NR; - Study beverage intake at baseline: 65 mL/d of soft drinks; Excluded from Study or Analysis: NR | Exposure: Soft drinks; Comparator: Dichotomous intake (≤65 mL/d versus >65 mL/d); Exposure Assessment Methods and Timing:; Validated semi-quantitative FFQ, assessed quantities and frequencies of soft drinks; At baseline, 18mo and 30mo follow-up; Outcomes and Assessment Methods:; - Height and weight measured by research team and used to calculate BMI and BMI z-scores based on Flemish reference data. Overweight cut-off point was BMI z-score of 1.; - At baseline, 18mo and 30mo follow-up | [underlined: Overweight by baseline SSB], OR (95% CI); 18mo follow-up (n=538); ≤65 mL/d: REF; >65 mL/d: 1.45 (0.85, 2.48); 30mo follow-up (n=473); ≤65 mL/d: REF; >65 mL/d: 1.36 (0.77, 2.40) | Model Adjustments:; - TEI: no; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position, anthropometry at baseline, physical activity, diet quality; - Other: none; Limitations:; - Only baseline exposure data used; No preregistered data analysis plan; Funding:; Ministry of the Flemish Community
Dong, 2015^17^; PCS, Avon Longitudinal Study pf Parents and Children (ALSPAC), UK; Analytic N=4,646; Included in meta-analysis: No; Participant characteristics at baseline: Children; - Age: 8y; - Female: 49%; - Race/ethnicity: NR; - SEP: NR; - Anthropometry: BMI, Mean: 16.2; BMI z-score, Mean: 0.1; - Physical activity: Mean (SD): 22.9 min/d (15.4) (at age 11y); - Diet quality: Mean (SD), g/d; - Fruit: 80; Vegetables: 74; Whole grains: 12; - TEI: NR; - Study beverage intake at baseline: Mean (SD), g/d; 7y: 82.2 (132.8); 10y: 106.9 (155.9); 13y: 131.9 (212.8); Excluded from Study or Analysis: Incomplete or missing dietary and anthropometric data at 7y, 10y, and 13y | Exposure: Normal fizzy drinks. Made-up squash. Normal squashes and cordials; Comparator: SSB (continuous; g/d): Per 100 g/d change over 3y, Per 100 g/d average across 3y; Exposure Assessment Methods and Timing: Three-day food diary, child report with help from parent; Represents current intake; Ages 7y, 10y, 13y; Outcomes and Assessment Methods:; - Height and weight measured by study personnel Calculated UK age and sex adjusted BMI z-score to represent adiposity; Excessive weight gain: increase in adiposity over 3y compared to reference group; BMI converted to g for interpretation (assumes 0.01 increase in BMI z-score = 50g); - Ages 7y, 10y, 13y | [underlined: Excess weight gain (g) over 3y], per 100 g/d increase (change-change model) or per 100 g/d intake (change-level model, average consumption) of SSB, Mean, linear regression; Change: β: 35, P<0.05; Average: β: −20, P=NS; Boys (n=2155); Change: β: 49, P<0.05; Girls (n=2193); Change: β: 22, P=NS; 7-10y period; Change: β: 43, P<0.10; 10-13y period; Change: β: 49, P<0.01 | Model Adjustments:; - TEI: no; - Key confounders: Sex, age, socioeconomic position (highest education level of child’s mother), physical activity; - Other: Pubertal status (Tanner stage); Limitations:; - Did not account for key confounders: Race and/or ethnicity, anthropometry at baseline, diet quality; - No info on missing data; no preregistered data analysis plan; Funding:; NR
Drenowatz, 2013^18^; PCS, Baden-Württemberg Study, Germany; Analytic N=1,249; Included in meta-analysis: No; Participant characteristics at baseline: children without overweight or obesity; - Age: ~7 (0.6)y; - Female: 49%; - Race/ethnicity: Migration background (at least one parent born outside Germany or the predominant language at home was not German): 23%; - SEP: NR; - Anthropometry: 100% without overweight or obesity; Height: ~123 cm; Weight: ~24 kg; BMI percentile, mean (SD): weight loss; group (n=330): 48.1 (21.5); constant weight; group (n=559): 39.6 (25.9); weight gain; group (n=360): 45.1 (22.7); - Physical activity: Habitual sports ~230 min/wk; Organized sports ~95 min/wk; - Diet quality: NR; - TEI: NR; - Study beverage intake at baseline: NR; Excluded from Study or Analysis: reported chronic disease; with overweight or obesity at baseline; lost to follow-up | Exposure: SSB (amount consumed per week); Comparator: categorical intake (regular soft drink consumption versus not); Exposure Assessment Methods and Timing:; Parent questionnaire; asked about the amount of SSB their children consumed per week; At baseline; Outcomes and Assessment Methods:; - Height and weight were measured by study personnel and used to calculate BMI percentiles using German reference values. Weight loss was based on a >5 reduction in BMI percentile, and weight gain was based on a >5 increase. Children with a ≤5 change in BMI percentile were classified as maintaining constant weight.; - At baseline, 1y follow-up | [underlined: Weight gain (versus weight loss) at 1y follow-up], OR (95% CI), multinomial logistic regression; No regular soft drink consumption: REF; Regular soft drink consumption: 1.01 (0.74, 1.39); [underlined: No change in weight (versus. weight loss) at 1y follow-up], OR (95% CI), multinomial logistic regression; No regular soft drink consumption: REF Regular soft drink consumption: 0.85 (0.64, 1.14) | Model Adjustments:; - TEI: no; - Key confounders: sex, anthropometry at baseline; - Other:; Limitations:; - Did not account for key confounders: age, race and/or ethnicity, socioeconomic position, physical activity, diet quality; - Exposure not well defined; Exposure data only measured at baseline; no information on non-completers; No preregistered data analysis plan; Funding:; Baden-Württemberg Stiftung
Dubois, 2007^19^; PCS, Longitudinal Study of Child Development in Québec, Canada; Analytic N=1,499; Included in meta-analysis: Yes; Participant characteristics at baseline: children; - Age: 2.5y; - Female: 51%; - Race/ethnicity: 41% immigrant; - SEP: 52% sufficient income level based on Statistics Canada low-income cut-offs; - Anthropometry: NR; - Physical activity: NR; - Diet quality: NR; - TEI: NR; - Study beverage intake at baseline: SSB intake at age 2.5y:; None: 58%; 1-3 times/wk: 22%; 4-6 times/wk: 6%; 1 times/d: 7%; ≥2 times/d: 7%; Excluded from Study or Analysis: missing data | Exposure: SSB (drinks with added sugar, including regular or non-diet carbonated drinks and fruit-flavored drinks such as fruit punch and orange drinks); excluding 100% fruit juices; Comparator: Categorical intake, by SSB consumption between meals (non-consumers, other, or regular consumers defined as 4-6 times/wk or more); “Other” group was not defined.; Exposure Assessment Methods and Timing: Self-administered FFQ completed by child’s mother: “In the past week, on average, how often during the week or how many times per day did your child have sugar-sweetened beverages as a snack between meals or immediately before bedtime.” Responses included none, one to three times per week, four to six times per week, one time per day, twice per day, three times per day, or four or more times per day. Children were defined as non-consumers, daily consumers, or regular consumers (four to six times per week or more) based on the responses. At 2.5, 3.5, and 4.5y; Outcomes and Assessment Methods:; - Weight and height measured by trained registered dietitians and used to calculate BMI. Overweight defined as BMI ≥95%tile on CDC sex- and age-specific growth charts; - At 4.5y | [underlined: Overweight at 4.5y by SSB intake between 2.5 and 4.5y], OR (95% CI), logistic regression; Non-consumers: REF; Others: 1.228 (0.770, 1.958); Regular consumers (4-6 times/wk): 2.356 (1.030, 5.390), p<0.05 | Model Adjustments:; - TEI: yes; - Key confounders: sex, age, socioeconomic position (income sufficiency), physical activity, diet quality (servings of fruits/vegetables, grain products, milk products, and meat and alternatives); - Other: Maternal smoking during pregnancy, birth weight, number of parents with overweight/obesity, carbohydrate intake, total fat intake; Limitations:; - Did not account for key confounders: race and/or ethnicity, anthropometry at baseline; - No information on non-completers; No preregistered data analysis plan; Funding:; Canada Research Chair Program; Canadian Institute of Health Information; Population Health Initiative; Canadian Institute of Health Research
Dubois, 2016^111^; PCS, Quebec Newborn Twin Study, Canada; Analytic N=304; Included in meta-analysis: No; Participant characteristics at baseline: Monozygotic (MZ) twin children; - Age: 9y (0.6); - Female: 55%; - Race/ethnicity: NR; - SEP: NR; - Anthropometry: BMI Mean (SD): 16.5 kg/m^2^ (2.5); - Physical activity: NR; - Diet quality: Food group intake, kcal/d, % of energy intake; Vegetables: 98, 5%; Fruit & fruit juice: 156, 9%; Whole grain: 86, 5%; Data for other food groups and macronutrients available in paper; - TEI: kcal/d, Mean (SD): 1,814 (393); - Study beverage intake at baseline: kcal/d, Mean (SD):; Sugary drinks: 74.22 (81.95); Soft drinks: 21.27 (42.48); Fruit drinks: 47.32 (64.32); Excluded from Study or Analysis: dietary data misreporting (Energy Intake:Basal Metabolic Rate ratios of <0.96 and >2.49) | Exposure: Sugary drinks, fruit drinks, soft drinks (kcal/d, % of total energy); Comparator: SSB (kcal), continuous; Exposure Assessment Methods and Timing: 24-hr recall performed by registered dietitians; Represents usual intake Baseline (9y); Outcomes and Assessment Methods:; - Height and weight self-reported except at baseline (measured); Intrapair difference (MZ twins) in BMI Discordant twins defined as ≥2 BMI units between pairs at least once at 9, 12, 13, and/or 14y; - Ages 9y, 12y, 13y, 14y | [underlined: Intrapair differences in BMI in subsequent years by intrapair differences in intake at 9y] (kcal or % energy), Spearman correlation; Sugary drink intake; All: kcal; % energy; 12y (n=238): −0.02, NS; −0.04, NS; 13y (n=226): −0.00, NS; −0.03, NS; 14y (n=212): −0.06, NS; −0.05, NS; Change 9-14y (n=210): −0.09, NS; −0.08, NS; Boys: kcal; % energy; 12y (n=102): −0.01, NS; 0.01, NS; 13y (n=96): 0.12, NS; 0.10, NS; 14y (n=92): −0.14, NS; −0.12, NS; Change 9-14y (n=92): −0.17, NS; −0.16, NS; Girls: kcal; % energy; 12y (n=136): −0.07, NS; −0.12, NS; 13y (n=130): −0.14, NS; −0.17, NS; 14y (n=120): 0.01, NS; −0.00, NS; Change 9-14y (n=108): −0.02, NS; −0.04, NS; Soft drink intake; All: kcal; % energy; 12y (n=238): 0.08, NS; 0.07, NS; 13y (n=226): 0.13, NS; 0.08, NS; 14y (n=212): 0.04, NS; 0.01, NS; Change 9-14y (n=210): 0.06, NS; 0.07, NS; Boys: kcal; % energy; 12y (n=102): 0.04, NS; 0.03, NS; 13y (n=96): 0.08, NS; 0.02, NS; 14y (n=92): 0.00, NS; −0.01, NS; Change 9-14y (n=92): 0.01, NS; 0.01, NS; Girls: kcal; % energy; 12y (n=136): 0.10, NS; 0.07, NS; 13y (n=130): 0.15, NS; 0.11, NS; 14y (n=120): 0.14, NS; 0.08, NS; Change 9-14y (n=108): 0.14, NS; 0.15, NS; Fruit drink intake; All: kcal; % energy; 12y (n=238): −0.11, NS; −0.10, NS; 13y (n=226): −0.12, NS; −0.12, NS; 14y (n=212): −0.13, NS; −0.13, NS; Change 9-14y (n=210): −0.12, NS; −0.11, NS; Boys: kcal; % energy; 12y (n=102): −0.08, NS: −0.04, NS; 13y (n=96): 0.07, NS; 0.07, NS; 14y (n=92): −0.12, NS; −0.11, NS; Change 9-14y (n=92): −0.13, NS: −0.12, NS; Girls: kcal; % energy; 12y (n=136): −0.15, NS; −0.17, NS; 13y (n=130): −0.28, NS; −0.26, NS; 14y (n=120): −0.16, NS; −0.18, NS; Change 9-14y (n=108): −0.09, NS; −0.11, NS; Refer to paper and supplemental data for additional analyses on:; - Comparison of Dietary Intake (at 9 years) Among Leaner and Heavier Twins From Discordant and Concordant MZ Twin Pairs; - Comparison of Dietary Intake at 9 Years Between Discordant MZ Twins for BMI at 9 Years and Older | Model Adjustments:; - TEI: no; - Key confounders: Sex, age, race and/or ethnicity, SEP, diet quality; - Other: None; Limitations:; - Did not account for key confounders: Anthropometry at baseline, physical activity; - No info on missing data; no preregistered data analysis plan; Funding:; Fonds Quebecois de la Recherche sur la Societe et la Culture; Fonds de la Recherche en Sante du Quebec; Social Science and Humanities Research Council of Canada; National Health Research Development Program; CIHR; Sainte-Justine Hospital Research Centre; Academy of Finland
Dubuisson, 2012^20^; RCS, Belgium Analytic N=144; Included in meta-analysis: No; Participant characteristics at baseline: Children enrolled in an obesity treatment intervention; - Age: 10.5 (3.1)y 73% <13y, 26% >13y; - Female: 59%; - Race/ethnicity: White (Caucasian): 73% ; Black (African): 2%; Asian (“Asiatic”): 2%; ; 10% “Arabian”; Hispanic: 12%; - SEP: NR; - Anthropometry: BMI z-score, mean (SD): 2.73 (0.62); - Physical activity: NR; - Diet quality: NR; - TEI: NR; - Study beverage intake at baseline: NR; Excluded from Study or Analysis: without obesity at baseline, participation in < 2 interdisciplinary visits, <1y of treatment, children with obesity due to organic/syndromic cause, type 2 diabetes | Exposure: soft drinks, no other details provided; Comparator: Categorical intake (no/low, intermediate, yes/high); Exposure Assessment Methods and Timing: Blinded consultant reviewed “standard homemade questionnaire” filled in by the team at baseline. Semiquantitative (low/intermediate/high) approach used to evaluate exposures. “No/low”=not every day or never, “Intermediate”=every day but at a low (1-2) level, “Yes/high”=every day at a high (>2) level.; Baseline (between 2002-2007); Outcomes and Assessment Methods:; - Weight and height measured by study staff, BMI (kg/m^2^) was expressed relative to the Cole population reference data. Weight loss was defined by reduction of the BMI standard deviation score (BMI-z-score); - Baseline, 9 mo | [underlined: Change in BMI-z-score after 9 months of intervention], mean (SE), quasilikelihood estimation, sandwich variance matrix No/low intake: −0.38 (0.06); Intermediate intake (1-2/d): −0.15 (0.03); High intake (>2/d): 0.08 (0.07) Between-group: p=0.00006 | Model Adjustments:; - TEI: no; - Key confounders: sex, age, anthropometry at baseline; - Other:; Limitations:; - Did not account for key confounders: race and/or ethnicity, socioeconomic position, physical activity, diet quality; - Exposure not well defined, Exposure assessment tool not validated; Exposure data only measured at baseline; no information on non-completers; No preregistered data analysis plan; Funding:; NR
Durao, 2015^21^; PCS, Generation XXI birth cohort, Portugal; Analytic N=589; Included in meta-analysis: No; Participant characteristics at baseline: children; - Age: 25.4 (1.1)mo; - Female: 50%; - Race/ethnicity: NR; - SEP: maternal education 10.9 (4.3)y; - Anthropometry: BMIz 0.7 (0.99); - Physical activity: NR; - Diet quality: 0.9 (0.9) frequency per day of energy dense foods; - TEI: NR; - Study beverage intake at baseline: NR; Excluded from Study or Analysis: twins, congenital anomalies or diseases (cerebral palsy, celiac disease, food allergy, food intolerance, phenylketonuria), missing data on covariables | Exposure: Soft drink intake (sweetened carbonated drinks and other sweetened drinks); Comparator: Continuous intake (times/d); Exposure Assessment Methods and Timing: FFQ answered by the primary caregiver; validated; At age 2y and 4y; Outcomes and Assessment Methods:; - Height and weight measured and used to calculate BMI and age- and sex-specific BMI z-scores (BMIz) according to the World Health Organization Child Growth Standards; - At age 2y and 4y | [underlined: BMIz at 4y by soft drink consumption at 2y]: Data NR, p=NS | Model Adjustments:; - TEI: no; - Key confounders: sex, age, socioeconomic position (education), anthropometry at baseline; - Other: maternal age, maternal pre-pregnancy BMI; Limitations:; - Did not account for key confounders: race and/or ethnicity, physical activity, diet quality; - No information on non-completers; No preregistered data analysis plan; Funding:; Programa Operacional de Sau´de—Sau´de XXI; Quadro Comunita´rio de Apoio III; Administrac¸a˜o Regional de Sau´de Norte (Regional Department of Ministry of Health); Portuguese Foundation for Science and Technology; Calouste Gulbenkian Foundation
Enes, 2013^24^; PCS, Brazil; Analytic N=256; Included in meta-analysis: Yes; Participant characteristics at baseline: adolescents; - Age: 11.8 (1.35)y; - Female: 56%; - Race/ethnicity: NR; - SEP: NR; - Anthropometry: BMI z-score, 0.4 (1.29); - Physical activity: 1.2 (1.07) hr/d; - Diet quality: 3.6 (2.2) svg/d fruits and vegetables; - TEI: 2418 (332) kcal/d; - Study beverage intake at baseline: 0.7 (1.0) svg/d sugar-sweetened drinks; 2.2 (0.8) svg/d sweetened fruit juice; Excluded from Study or Analysis: missing data, loss to follow-up, BMI or annual BMI change >3 SD and decrease in height, | Exposure: Sugar-sweetened beverages (e.g., regular soda, coffee, sweetened iced tea, noncarbonated fruit drinks) and sweetened fruit juices (natural fruit juices with added sugar); Comparator: Continuous intake (svg/d); Exposure Assessment Methods and Timing:; Validated FFQ representing usual intake over the past 6mo; At baseline, 1y follow-up; Outcomes and Assessment Methods:; - Height and weight measured by study staff and used to calculate BMI. BMI z-score converted from BMI using WHO growth reference for school-aged children and adolescents; - At baseline, 1y follow-up | [underlined: Change in BMIz by change in SSB (svg/d) over 1y], β (95% CI); Sweetened fruit juices: 0.053 (0.004, 0.102), p=0.03; Sugar-sweetened drinks: Data NR, p=NS | Model Adjustments:; - TEI: no; - Key confounders: sex, age, anthropometry at baseline; - Other: interval between study interviews, sexual maturation; Limitations:; - Did not account for key confounders: race and/or ethnicity, socioeconomic position, physical activity, diet quality; - High attrition/missing data; No preregistered data analysis plan; Funding:; State of Sao Paulo Research Support Foundation
English, 2022^25^; PCS, Early Life Exposure in Mexico to Enviromental Toxicants (ELEMENT) cohort, Mexico; Analytic N=464; Included in meta-analysis: Yes; Participant characteristics at baseline: children and adolescents; - Age: 33% 9 to <13y; 34% 13 to <16y; 33%≥16y; - Female: 53%; - Race/ethnicity: NR; - SEP: SES status: Higher: 20%; Medium: 31%; Lower 49%; - Anthropometry: NR; - Physical activity: Physical activity (min/d), by quartiles (n=116 in each quartile): Q1: 15-53; Q2: 54-70; Q3: 70-91; Q4: 91-216; - Diet quality: NR; - TEI: NR; - Study beverage intake at baseline: Median (IQR): 303 mL (462 mL); males: median 343 mL/d, females: median 269 mL/d; Excluded from Study or Analysis: incomplete information on sociodemographic characteristics, dietary intake, physical activity, anthropometry, and pubertal development at both time points | Exposure: Corn atole, flavored water and drinks with sugar, chocolate milk, soda, tea and coffee with sugar, and sugar-sweetened probiotic milk beverages; Comparator: Categorical intake, by change in intake over 2y: Decrease ≥480 mL (n=53); decrease 240 to <480 mL (n=77); decrease <240 mL (n=134); no change to increase <240 mL (n=145, reference group); increase 240 to <480 mL (n=37); increase ≥480 mL (n=28); Exposure Assessment Methods and Timing: FFQ adapted from 2006 Mexican Health and Nutrition Survey, administered by trained professional; asked about consumption of foods and beverages by days/wk (never to 7 days). If consumption was noted every day, participants were asked about number of times/d (1 to ≥6). Intake expressed in mL/d; change in SSB consumption calculated as intake in 2017 minus intake in 2015.; Baseline (2015), 2y follow-up (2017); Outcomes and Assessment Methods:; - Weight and height measured using standard procedures by study staff; BMI was calculated as kg/m2. Body fat percentage was assessed by bioelectrical impedance equipment. Waist circumference measured by study staff using standard methods (measuring tape).; - Baseline (2015), 2y follow-up (2017) | [underlined: Body fat % change over 2y by change in SSB consumption], β (95% CI), linear regression; No change to increase <240 mL: REF; Increase ≥480 mL: 2.72 (0.61, 4.82), P<0.05; P=NS for all other change categories compared with reference group; p-trend=0.008; Stratified by pubertal stage Early Puberty (n=148):; No change to increase <240 mL: REF; Increase 240 to <480 mL: 4.72 (0.43, 8.99), p<0.05; Increase ≥480 mL: 4.90 (0.19, 9.60), p<0.05; P=NS for all other change categories compared with reference group; p-trend=0.029; Mid Puberty (n=223): P=NS for all change categories compared with reference group; p-trend=0.159; Post Puberty (n=93):; Increase 240 to <480 mL: 5.63 (2.45, 8.80), p<0.05; P=NS for all other change categories compared with reference group; p-trend=0.014; [underlined: WC change over 2y by change in SSB consumption], cm, β (95% CI), linear regression; Increase 240 to <480 mL: 2.49 (0.21, 4.76), p<0.05; P=NS for all other change categories compared with reference group; p-trend=0.023; Stratified by pubertal stage; Early Puberty (n=148): P=NS for all change categories compared with reference group; p-trend=0.073; Mid Puberty (n=223): P=NS for all change categories compared with reference group; p-trend=0.434; Post Puberty (n=93):; Increase 240 to <480 mL: 6.51 (1.26, 11.76), p<0.05; P=NS for all other change categories compared with reference group; p-trend=0.109; BMI change over 2y by change in SSB consumption, β (95% CI), linear regression P=NS for all change categories compared with reference group; p-trend=0.139; Stratified by pubertal stage; Early Puberty: P=NS for all change categories compared with reference group; p-trend=0.146; Mid Puberty: P=NS for all change categories compared with reference group; p-trend=0.405; Post Puberty: P=NS for all change categories compared with reference group; p-trend=0.545 | Model Adjustments:; - TEI: no; - Key confounders: sex, age, socioeconomic position, anthropometry at baseline, physical activity; - Other: Screen time, change in age between two assessments; Limitations:; - Did not account for key confounders: race and/or ethnicity, diet quality; - Changes in exposure were not balanced across groups; High attrition/missing data with no information on non-completers; No preregistered data analysis plan; Funding:; US EPA, NIEHS; National Institute of Public Health/Ministry of Health of Mexico
Faith, 2006^26^ PCS, U.S.; Analytic N=825; Included in meta-analysis: Yes; Participant characteristics at baseline: Young children; - Age: 30.2 (9.0) mo; - Female: 47%; - Race/ethnicity: Non-Hispanic White: 36%; Non-Hispanic Black: 21%; Other: 9%; Hispanic: 35%,; - SEP: Parent education: <High school: 31%, High school: 40%, >High school: 29%; - Anthropometry: At risk for overweight (>85th-94th percentile): 15.6%; Overweight (>95th percentile): 17.3%; - Physical activity: NR; - Diet quality: Svg/d, Mean (SD):; Vegetables (excluding potatoes and carrots): 1.7 (0.9; Fruits (excluding juice): 2.3 (1.0); - TEI: NR; - Study beverage intake at baseline: Mean ~3.0 svg/d; Excluded from Study or Analysis: not currently participating in WIC, age <1y or >5y at baseline; missing race/ethnicity data | Exposure: Fruit juice (Not clear if 100% fruit juice) (serving=3/4 cup); Comparator: Continuous intake, svg/d; Exposure Assessment Methods and Timing: Non-validated parent-report questionnaire of usual daily intake; Baseline; Outcomes and Assessment Methods:; - Weight was measured by WIC staff using a standard balance-beam scale Height for children >36in tall or >2y measured with stadiometer; otherwise, length was measured using a recumbent board; length converted to height by subtracting 0.5cm; BMI, BMI z-score, weight-for-height-Z computed with CDC growth charts Change in adiposity: defined as change in age- and gender-standardized BMI per month (i.e., BMI z-score slope) Categorical: ≥85th percentile = at risk for overweight or overweight; <85th percentile = not at risk or overweight; - Every 6mo for 18-48mo | [underlined: Change in adiposity per svg/d increase], Multivariate linear regression, β (SE); Pooled (n=825): 0.005 (0.002), P<0.01; At risk/overweight (n=264): 0.009 (0.003), P<0.01; (Boys showed greater increase than girls, P=0.04; additional data NR); Not at risk/overweight (n=561): 0.003 0.002), P=0.13 | Model Adjustments:; - TEI: no; - Key confounders: Sex, age, race and/or ethnicity, anthropometry at baseline, diet quality; - Other: Food group intake, parental feeding behaviors; Limitations:; - Did not account for key confounders: socioeconomic position, physical activity; - Exposure assessment not validated; exposure assessed at baseline only; no info on missing data; no preregistered data analysis plan; Funding:; USDA
Field, 2014^27^; PCS, Growing Up Today Study (GUTS) II cohort, U.S.; Analytic N=7,559; Included in meta-analysis: Yes; Participant characteristics at baseline: Children and adolescents; - Age: ~13y; - Female: 55%; - Race/ethnicity: NR; - SEP: NR; - Anthropometry: Mean BMI ~20 kg/m^2^; ~20% overweight; - Physical activity: vigorous: ~7h/w; - Diet quality: NR; - TEI: NR; - Study beverage intake at baseline: NR; Excluded from Study or Analysis: age < 9y or >15 y at baseline; data on BMI from <2 consecutive questionnaires; missing information on vigorous activity or reported >40h/wk vigorous activity; missing information on time spent watching TV, missing information on sports drink or diet soda consumption | Exposure: regular soda, sports drinks; assessed as # cans (soda) or bottles (sports drinks)/d but exact serving size is not specified; Comparator: continuous; svg/d; Exposure Assessment Methods and Timing: Youth/Adolescent questionnaire; validated Baseline, 2y, 4y, 7y; Outcomes and Assessment Methods:; - Weight and height self-reported; BMI calculated as kg/m2; - Baseline, 2y, 4y, 7y | [underlined: Change in BMI with baseline intake and change in intake], β (95% CI); [Note: change in intake was adjusted for baseline intake in these results. Analyses looking at only baseline intake or change in intake without adjusting for baseline are presented in the paper]; Girls:; Regular soda: 0.02 (−0.14, 0.19); Change in soda: 0.12 (−0.05, 0.29); Sports drinks: 0.29 (0.03, 0.54); Change in sports drinks: 0.05 (−0.19, 0.29); Boys:; Regular soda: 0.09 (−0.06, 0.24); Change in soda: 0.14 (−0.02, 0.30); Sports drinks: 0.33 (0.09, 0.58); Change in sports drinks: 0.43 (0.19, 0.66) | Model Adjustments:; - TEI: no; - Key confounders: sex, age, anthropometry at baseline, physical activity; - Other: Tanner stage of development (boys only), hours per day of television viewing, time between assessments, baseline and change values for other 2 beverages of interest; Limitations:; - Did not account for key confounders: race and/or ethnicity, socioeconomic position, diet quality; - High attrition and no information on non-completers; weight and height were self-reported; No preregistered data analysis plan; Funding:; Breast Cancer Research Foundation and NIH
Fiorito, 2009^28^; PCS, U.S.; Analytic N=166; Included in meta-analysis: Yes; Participant characteristics at baseline: Female children; - Age: 5y; - Female: 100%; - Race/ethnicity: “Predominantly non-Hispanic white”; - SEP: Paternal education, 14.9y (2.7); Maternal education, 14.8y (2.3); Family income, averaged $50,000-$75,000; - Anthropometry: Mean (SD): BMI for age percentile, 59.3 (26.6); Body fat %, 20.6 (4.3); Overweight 18%; - Physical activity: NR; - Diet quality: NR; - TEI: NR; - Study beverage intake at baseline: NR; Excluded from Study or Analysis: incomplete dietary intake and body weight data at ≥2/6 measurement occasions, not living with both biological parents, severe food allergies or chronic medical problems affecting food intake, dietary restrictions involving animal products | Exposure: any sugar-sweetened or artificially sweetened fruit-flavored drinks, sports (natural or artificial) drinks, and drinks that contained <100% fruit juice; sodas that included carbonated sugar-sweetened or artificially sweetened, caffeinated or decaffeinated colas; sugar-sweetened or artificially sweetened, caffeinated or decaffeinated tea or coffee. 1 svg=8 ounces; Comparator: Continuous intake; categorical intake (<1, ≥1 and <2, or ≥2 svg/d); Exposure Assessment Methods and Timing:; Three, 24-hr recalls (2 weekdays, 1 weekend day) within 2- to 3-wk period conducted by trained staff using NDS-R software and reported by mother; represents usual intake; Baseline; Outcomes and Assessment Methods:; - Body fat % estimated by tricep and subscapular skinfold thickness at age 5, 7, 9, and 11y and DXA scans at age 9, 11, 13 and 15; - At 7, 9, 11, 13, 15y | [underlined: Body fat percentage], β, linear regression Unadjusted; 7y (N=169): 0.27, p<0.0001; 9y (N=158): 0.32, p<0.0001; 11y (N=164): 0.23, p<0.01; 13y (N=150): 0.20, p<0.05; 15y (N=160): 0.18, p<0.05; Adjusted for SSB intake at the age adiposity was measured; 7y (N=169): 0.29, p<0.01; 9y (N=158): 0.30, p<0.01; 11y (N=164): 0.20, p<0.05; 13y (N=150): 0.21, p<0.05; 15y (N=160): 0.17, p<0.05; Adjusted for energy intake at age 5y; 7y (N=169): 0.26, p<0.01; 9y (N=158): 0.29, p<0.01; 11y (N=164): 0.20, p<0.05; 13y (N=150): 0.20, p<0.05; 15y (N=160): 0.18, p<0.05; Adjusted for parental education at study entry; 7y (N=169): 0.23, p<0.01; 9y (N=158): 0.24, p<0.01; 11y (N=164): 0.16, p<0.05; 13y (N=150): 0.12, p=NS; 15y (N=160): 0.08, p=NS; Adjusted for family income at study entry; 7y (N=169): 0.28, p<0.01; 9y (N=158): 0.30, p<0.01; 11y (N=164): 0.23, p<0.01; 13y (N=150): 0.21, p<0.05; 15y (N=160): 0.18, p<0.05; Categorical analyses [NOTE: full data available in Table 4 of paper], mixed modeling ANOVA; [underlined: Body fat %]; Main effect for beverage intake category: p<0.01; Main effect for age: p<0.01 group x age interaction: p<0.01; [underlined: Waist circumference]; Main effect for beverage intake category: p<0.05; Main effect for age: p<0.01; group x age interaction: p=NS; [underlined: BMI-for-Age percentile], mean (SD); <1, ≥1 and <2, ≥2 svg/d; mixed modeling ANOVA; 7y: 56 (27), 56 (27), 69 (29); 9y: 61 (27), 63 (27), 77 (22); 11y: 60 (27), 64 (29), 75 (23); 13y: 60 (26), 62 (25), 71 (27); 15y: 60 (26), 60 (24), 67 (25); Main effect for beverage intake category: p<0.05; Main effect of age: p=NS; Group x age interaction: p=NS; [underlined: Overweight], %, <1, ≥1 and <2, ≥2 svg/d; mixed modeling ANOVA; 7y: 15, 12, 46; 9y: 24, 29, 42; 11y: 22, 29, 54; 13y: 22, 20, 46; 15y: 19, 18, 32; Main effect for beverage intake category: p<0.01; Main effect of age: p=NS; Group x age interaction: p=NS | Model Adjustments:; - TEI: no; - Key confounders: Sex, age; - Other: none; Limitations:; - Did not account for key confounders: race and/or ethnicity, SEP, anthropometry at baseline, physical activity, diet quality; - Possible reporting bias (not all outcome measures reported for each beverage type); no preregistered data analysis plan; Funding:; NIH; The National Dairy Council
French, 2012^29^; PCS, Secondary analysis of Take Action RCT, U.S.; Analytic N=72; Included in meta-analysis: No; Participant characteristics at baseline: Adolescents; - Age: ~14.7y; - Female: 39%; - Race/ethnicity: ~77% white; - SEP: 60% with adults in household with college, grad or prof degree; 43% with household income ≤$45K; 31% >$45K-100K; 26% ≥$100K; - Anthropometry: Median BMI z-score: ~0.71; - Physical activity: Median ~105 in moderate/vigorous physical activity score; - Diet quality: Fast food restaurant: Median 0.5 times/wk; - Eating out: Median 2 times/wk; - TEI: NR; - Study beverage intake at baseline: Median: ~0.28 portions SSB/wk; Excluded from Study or Analysis: < one adult and two household members (including the adult) ages >12y; not residing in a private house or apartment within 20 miles of university; household TV viewing weekly average of ≤10hr per person; any household members with dietary, medical, psychological, or physical limitations that would prevent participation in intervention; not willing to be randomized to active intervention or control | Exposure: SSBs (fruit drinks, such as cranberry cocktail, Hi-C, lemonade, or Kool-Aid; regular (non-diet) soft drinks, soda, or pop); Comparator: Categorical intake, by difference between intake at 12mo and baseline, portions/wk: Decrease versus. No change/increase; Exposure Assessment Methods and Timing: Modified FFQ; intake over past month; validation not clear Baseline, 12mo (after 12mo intervention); Outcomes and Assessment Methods:; - Height and weight measured by trained research staff; age- and sex-specific BMI z-score calculated using Lambda-Mu-Sigma method; Obesity defined as BMI>30 kg/m2; - Baseline, 12mo | [underlined: Change in BMI z-score per SSB change over 12mo], least-squares mean (SE), mixed model regression; Decrease (n = 28): 0.75 (0.08); No change/increase (n = 38): 0.75 (0.07) P=0.99 | Model Adjustments:; - TEI: no; - Key confounders: sex, age, socioeconomic position (highest education in household, household income), anthropometry at baseline; - Other: Treatment group, household identification number, baseline SSB intake; Limitations:; - Did not account for key confounders: race and/or ethnicity, physical activity, diet quality; - Unclear if exposure assessment tool is validated; Attrition and bias due to missing data can’t be determined because baseline n NR; No preregistered data analysis plan; Funding:; NIH, NCI
Goff, 2019^32^; PCS, Determinants of Adolescent Social wellbeing and Health (DASH) cohort, UK; Analytic N=665; Included in meta-analysis: Yes; Participant characteristics at baseline: children and adolescents; - Age: NR; - Female: 51%; - Race/ethnicity: White British: 16%; Black African: 20%, Black Caribbean: 15%; Bangladeshi/Pakistani: 17%, Indian: 15%; Other (mainly mixed ethnicity): 17%; - SEP: NR; 47% with university degree at follow-up; - Anthropometry: NR; 39% with overweight or obesity at follow-up; - Physical activity: NR; ~738 min/d sedentary time at follow-up; - Diet quality: NR; - TEI: NR; 2192 (2097-2288) kcal/d at follow-up; - Study beverage intake at baseline: NR; Excluded from Study or Analysis: NR | Exposure: SSB (“fizzy drinks: like coke, pepsi”); Comparator: categorical intake (everyday/most days versus weekly/<weekly/never); Exposure Assessment Methods and Timing: “How often do you usually eat or drink the following: fizzy drinks like coke, pepsi?” (every day, most days, weekly, less than weekly, never). Responses were recoded as consuming fizzy drinks every day or most days.; At baseline (11-13y); Outcomes and Assessment Methods:; - Weight and height were measured by study personnel and used to calculate BMI. Waist circumference was measured by study personnel and used to calculate waist:height ratio.; - At 21-23y | [underlined: Waist:Height ratio at 21-23y based on SSB intake at 11-13y], β (95% CI); Weekly/<weekly/never: REF; Everyday/most days: 0.001 (−0.01, 0.01), p=0.888; [underlined: BMI at 21-23y based on SSB intake at 11-13y], β (95% CI); Weekly/<weekly/never: REF; Everyday/most days: 0.03 (−0.89, 0.84), p=0.947 | Model Adjustments:; - TEI: yes; - Key confounders: sex, race and/or ethnicity, socioeconomic position, physical activity; - Other: Saturated fat intake at follow-up; smoking at follow-up; Limitations:; - Did not account for key confounders: age, anthropometry at baseline, diet quality; - Exposure data only measured at baseline; High attrition with no information on non-completers; No preregistered data analysis plan; Funding: Medical Research Council, Chief Scientist Office, North Central London Research Consortium; Primary Care Research Network
Gopinath, 2013^34^; PCS, Sydney Childhood Eye Study, Australia; Analytic N=1,213; Included in meta-analysis: Yes; Participant characteristics at baseline: adolescents; - Age: ~12y; - Female: 49%; - Race/ethnicity: ~63% Caucasian; - SEP: ~53% parent with tertiary education; - Anthropometry: BMI ~20 kg/m^2^; - Physical activity: ~0.85 h/d; - Diet quality: ~240 g/d fruits, ~158 g/d vegetables; - TEI: NR; - Study beverage intake at baseline: ~48% soft drinks ≤1/wk; Excluded from Study or Analysis: missing data, loss to follow-up | Exposure: Soft drinks (unclear if also included cordials, a sweet flavored concentrated syrup that is mixed with water to taste); Comparator: Categorical intake (Never/rarely, ≤1 time/wk, 2-6 times/wk, ≥1/day); Exposure Assessment Methods and Timing: FFQ answered by the child; At baseline, 5y follow-up; Outcomes and Assessment Methods:; - Weight and height were measured at school and used to calculate BMI. WC was measured. Body fat percentage was measured using a Tanita body composition analyzer.; - At baseline, 5y follow-up | [underlined: Change in body fat % over 5y by baseline soft drink intake], β; Girls; Never/rarely: −0.66; ≤1 time/wk: data NR; 2-6 times/wk: data NR; ≥1/day: 3.79; p-trend=0.01 Boys; Data NR, p=NS; [underlined: Change in WC (cm) by baseline soft drink intake], β; Girls; Never/rarely: 6.46; ≤1 time/wk: data NR; 2-6 times/wk: data NR; ≥ 1/day: 10.00; Never/rarely versus ≥ 1/day: p=0.004; p-trend=NS; Boys; Data NR, p=NS; [underlined: Change in BMI (kg/m2) by baseline soft drink intake], β; Girls; Never/rarely: 1.96; ≤1 time/wk: data NR; 2-6 times/wk: data NR; ≥ 1/day: 3.20; Never/rarely versus ≥ 1/day: p=0.01; p-trend=NS; Boys; Data NR, p=NS | Model Adjustments:; - TEI: yes; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position (parental education), anthropometry at baseline, physical activity; - Other: exposure to passive smoking, screen viewing time; Limitations:; - Did not account for key confounders: diet quality; - Only baseline exposure data used in analysis; High attrition/missing data; No preregistered data analysis plan and did not report results for boys; Funding: Australian National Health & Medical Research Council; Westmead Millennium Institute, University of Sydney; Vision Co-operative Research Centre, University of New South Wales; National Heart Foundation of Australia
Guerrero, 2016^35^; PCS, Early Childhood Longitudinal Study-Birth Cohort (ECLS-B), U.S.; Analytic N=15,418; Included in meta-analysis: Yes; Participant characteristics at baseline: Children; - Age: ~53 (4.1) mo; - Female: 49%; - Race/ethnicity: White: 43%; Black: 16%; Asian: 11%; Other: 10%; Native American: NR; Latino: 20%; Hispanic: NR; Non-Hispanic: NR; 9% Spanish-speaking; - SEP: Maternal education: 21% High school, 27% College, 31% ≥Bachelor; Income: ~24% below fed poverty level; 79% lived in 2-parent households; Mother’s acculturation (# years in USA), mean (SD): 27.6 (10.4)y; - Anthropometry: Mean BMI ~16.5 kg/m^2^; ~47% with overweight or obesity at baseline; - Physical activity: NR; - Diet quality: Consumption in last week (% Yes); Data from n=7696 included at 48-mo wave (baseline); Any fast food: 75.4%; Fruit 7 times/wk: 71.7%; Vegetables 7 times/wk: 68.4%; - TEI: NR; - Study beverage intake at baseline: Any soda in past week (age 48mo): ~71.3%; Excluded from Study or Analysis: incomplete data on weight and height; mothers not able to be interviewed; serious birth defects (such as spina bifida or heart defects) or who died before 5y | Exposure: Soda; Comparator: Soda intake, categorical: Any intake in the last 7d versus. No intake in the last 7d; Exposure Assessment Methods and Timing: Parental interview: “Was soda consumed in past 7d? Yes/No” 48, 60, and 72 mo; Outcomes and Assessment Methods:; - Height and weight obtained by trained researchers using standardized procedures and equipment. Age- and sex- specific BMI percentiles calculated using 2000 CDC growth charts; Overweight: BMI 85th-<95th percentile; Obesity: BMI ≥95% percentile; - 48, 60, and 72 mo | [underlined: BMI trajectory], Hierarchical linear modeling, β (SE); No soda (ref) versus; Soda within 7d: 0.138 (0.037), P<0.05; By race: No soda (ref) versus soda within 7d; β (SE); White: 0.087 (0.054), NS; Black: 0.288 (0.107), P<0.01; Asian: 0.065 (0.100), NS; Hispanic-English: 0.027 (0.139), NS; Hispanic-Spanish: 0.234 (0.115), P<0.05 | Model Adjustments:; - TEI: no; - Key confounders: Sex, age, race and/or ethnicity, socioeconomic position, diet quality (daily servings of fruits and vegetables); - Other: Birth weight, breastfeeding during infancy; Limitations:; - Did not account for key confounders: Anthropometry at baseline, physical activity,; - Exposure not well defined (does not account for amount of exposure (just Y/N within 7d); Exposure assessment tool not validated; Baseline, analytic sample sizes, and attrition not clear; No preregistered data analysis plan; Funding: HHS; University of California’s Institute of Human Development; McCormick Foundation
Haines, 2007^36^; PCS, U.S.; Analytic N=2,516; Included in meta-analysis: Yes; Participant characteristics at baseline:; Adolescents; - Age: Mean (SD): Middle school cohort, 12.8 (0.8)y; High school cohort, 15.8 (0.8) y Middle school cohort = 1/3 of participants; High school = 2/3; - Female: 55%; - Race/ethnicity: white: 48.3% ; Black: 18.9%; Asian: 19.6%; Native American: 3.6%, mixed race or other: 3.8%; Hispanic: 5.8%; - SEP: Low or low-middle SES, 37%; - Anthropometry: BMI (Mean, kg/m^2^), Girls 22.4, Boys 22.5; Overweight (>85th percentile), Girls 25.7%, Boys 26.4%; - Physical activity: Moderate and vigorous physical activity, Mean (SD): Girls: 5.8 hr/wk (4.7); Boys: 7.4 hr/wk (4.7); - Diet quality: Fruits and vegetables, serv/d, Mean (SD) Girls: 4.2 (2.9) Boys: 3.8 (2.9); - TEI: Mean (SD), kcal/d: Girls: 1,994 (1047); Boys: 2,249 (1,216); - Study beverage intake at baseline: Total SSB, Mean (SD) Girls: 0.6 (0.6) svg/d Boys: 0.7 (0.7) svg/d; Excluded from Study or Analysis: not in middle or high school in 1998-1999; missing survey at baseline or 5y | Exposure: Gatorade, regular soda pop, Hawaiian Punch/lemonade/Kool-Aid/other non-carbonated fruit drinks; Comparator: Continuous intake; Exposure Assessment Methods and Timing:; 149 item semi-quantitative Youth and Adolescent FFQ (YAQ); Represents usual intake; Baseline, 5y follow up; Outcomes and Assessment Methods:; - Weight and height self-reported Overweight defined as BMI >85th percentile for age and gender, using Must et al. classification; - Baseline, 5y follow up | [underlined: Overweight at 5y follow-up], OR (95% CI), linear regression; Girls:; Baseline intake: 1.34 (1.00, 1.81); Change in intake: Data NR, p=NS; Boys:; Baseline intake: 0.82 (0.58, 1.17); Change in intake: Data NR, p=NS; [underlined: Incident overweight], OR (95% CI), linear regression; Girls:; Baseline intake: 1.41 (0.95, 2.12); Change in intake: Data NR, p<0.05; ("increases of servings of sugar-sweetened beverages was a risk factor"); Boys:; Baseline intake: 0.63 (0.37, 1.07); Change in intake: Data NR, p<0.05 | Model Adjustments:; - TEI: yes; - Key confounders: Sex, age, race and/or ethnicity, SEP (parental education level), anthropometry at baseline (baseline overweight status); - Other: Cohort; Limitations:; - Did not account for key confounders: Physical activity, diet quality; - No info on missing data; self-reported outcome data (height and weight); no preregistered data analysis plan; Funding:; Maternal and Child Health Bureau (HHS)
Hasnain, 2014^37^; PCS, Framingham Children’s Study, U.S.; Analytic N=98; Included in meta-analysis: No; Participant characteristics at baseline:; Children; - Age: NR; - Female: 55%; - Race/ethnicity: Non-Hispanic White: 100%; - SEP: Maternal education >college, ~34%; 100% 2-parent household; - Anthropometry: BMI, Mean ~16.1 kg/m^2^; - Physical activity: Caltrac counts/hr, Mean: ~10.7; - Diet quality: NR; - TEI: Mean~1724 kcal/d; - Study beverage intake at baseline:; Excluded from Study or Analysis: missing exposure data at age 3-9y; missing anthropometry data at 15-17y | Exposure: SSB: sweetened carbonated beverages, sweetened noncarbonated beverages, sweetened tea or coffee, partjuice beverages; Fruit and vegetable juice: unsweetened fruit juice, small amounts of vegetable juice and sweetened fruit juice; Comparator: Categorical intake, by tertile, mean (SD): SSB: T1:2.8 (1.2) oz/d, T2: 5.8 (0.9) oz/d, T3: 10.7 (2.6) oz/d; Fruit/vegetable juice: T1: 1.9 (1.0) oz/d; T2: 4.9 (1.2) oz/d, T3: 10.2 (2.8) oz/d; Exposure Assessment Methods and Timing:; Up to 4 sets of 3-d diet records annually completed by parents (up to age 10y) or children (after age 10y); Represents usual intake; Baseline (3-5y), annually for 12y (age 15-17y); Outcomes and Assessment Methods:; - Weight, height, waist circumference measured by study personnel Four skinfolds (triceps, subscapular, suprailiac, abdominal) measured in duplicate following standard protocol Percent body fat measured with DXA scan (end of follow-up only); - At baseline (3-5y), annually for 12y (age 15-17y) | [underlined: Effects of intake (by tertiles) at ages 3-9y on] [underlined: outcomes at end of follow-up (ages 15-17y);] linear regression; [underlined: SSB]; Body fat %, Data NR, p=0.9296; Sum of 4 skinfolds, mm: Data NR, p=0.9790; WC, cm: Data NR, p=0.3494; Fruit/vegetable juice:; Body fat %, Data NR, p=0.1199; Sum of 4 skinfolds, mm: Data NR, p=0.0383; WC, cm: 8cm, p=0.0328; Effects of intake (by tertiles) on sum of 4 skinfolds over time; mixed model SSB; T1 versus T2: Data NR, p=0.1121; T1 versus T3: Data NR, p=0.8807; T2 versus T3: Data NR, p=0.0737; Fruit/vegetable juice; T1 versus T2: Data NR, p=0.0984; T1 versus T3: Data NR, p=0.0001; T2 versus T3: Data NR, p=0.0201; Effects of intake (by tertiles) at ages 3-9y on BMI (kg/m2) at end of follow-up (ages 15-17y); linear regression; SSB: Data NR, p=0.4204; Fruit/vegetable juice: Data NR; p=0.0626 | Model Adjustments:; - TEI: yes and no; - Key confounders: Sex, age, race and/or ethnicity, socioeconomic position (maternal education), anthropometry at baseline (baseline body fat), physical activity; - Other: Percent of calories from fat, mean TV and video time, maternal education, maternal BMI; Limitations:; - Did not account for key confounders: diet quality; - Exposure assessment validity unclear; no preregistered data analysis plan; Funding:; NHLBI; National Dairy Council
He, 2022^38^; PCS, China; Analytic N=5,963; Included in meta-analysis: Yes; Participant characteristics at baseline:; Children; - Age: 10.7 (2.2)y; - Female: 50%; - Race/ethnicity: Han: 99.2% ; Minority: 0.8%; - SEP: <1000 yuan/mo: 2%; 1,000-5,000: 19%; 5,000-10,000: 42%; 10,000-20,000: 26%; ≥20,000: 12%; Paternal & maternal career category can be found in paper; - Anthropometry: BMI, mean (SD): 18.4 (3.2) kg/m^2^ Underweight: 1% Normal weight: 81% Overweight: 9% Obesity: 9%; - Physical activity: Mean (SD): 90.4 (50.9) min/d; - Diet quality: NR; - TEI: NR; - Study beverage intake at baseline: Mean (SD): 1.5 (1.9) times/wk; Excluded from Study or Analysis: NR | Exposure: Sugar-sweetened beverages (no further details given); Comparator: Continuous intake, times/wk; Exposure Assessment Methods and Timing:; Chengdu Positive Child Development (CPCD) survey; completed by the child; assessed SSB consumption over past week; Baseline (pre-COVID-19 pandemic), 6mo follow up (during pandemic); Outcomes and Assessment Methods:; - Height and weight measured by hospital technicians at baseline; reported by parents at follow-up due to COVID-19. Weight status based on WHO age- and sex-specific BMI thresholds; - Baseline (pre-COVID-19 pandemic), 6mo follow up (during pandemic) | [underlined: Risk of obesity at 6mo follow up], generalized estimating equation, β (SE), OR; Sugar-sweetened beverage consumption: 0.009 (0.011), 1.004, p=0.441 | Model Adjustments:; - TEI: No; - Key confounders: Sex, age, race and/or ethnicity, physical activity; - Other: District (rural or urban), Education (primary or secondary school), COVID-19 infection history, sleep duration, screen time; Limitations:; - Did not account for key confounders: socioeconomic position, anthropometry at baseline, diet quality; - Exposure not well defined; Exposure tool not validated; Follow-up outcome data were selfreported; Context of the study (pre- and during-COVID-19 pandemic) creates a unique situation with limited generalizability; No preregistered data analysis plan; Funding:; The Hong Kong Polytechnic University, the Science and Technology Department of Sichuan Province, China
Hooley, 2012^39^; PCS, Longitudinal Study of Australian; Children (LSAC), Australia; Analytic N=4,149; Included in meta-analysis: Yes; Participant characteristics at baseline: Children; - Age: ~4.8y; - Female: 48%; - Race/ethnicity: NR; - SEP: NR; - Anthropometry: BMI z-score 0.55; 21% with overweight or obesity; - Physical activity: NR; - Diet quality: NR; - TEI: NR; - Study beverage intake at baseline: High-sugar drinks at baseline: 1.7 times/d; Excluded from Study or Analysis: >5y during wave 1 (2004), missing outcome data | Exposure: High-sugar drinks (HSD; fruit juice, soft drink or cordial; not diet); Comparator: Continuous intake, times/d; Exposure Assessment Methods and Timing:; “Time use diaries”: Parent-reported frequency of consumption in the 24 h prior to the survey; not validated Baseline, 2y, 4y; Outcomes and Assessment Methods:; - Weight and height measured; Waist circumference (WC) measured horizontally around naval with non-stretch tape. Classified as underweight, normal weight, with overweight or with obesity according to the International Obesity Task Force age- and sex-specific criteria for BMI.; - Baseline, 2y, 4y | [underlined: Weight status at 4y follow-up], association with sweet drink intake at 2y follow-up (not baseline): RRR (least squares error); Thin: 1.07 (0.10), P=0.43; Normal: ref; With overweight/obesity: 1.10 (0.05), P=0.02 | Model Adjustments:; - TEI: no; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position; - Other: Breastfed, frequency of tooth brushing, maternal BMI, maternal age, maternal smoking during pregnancy, alcohol during pregnancy, number of smokers in household; Limitations:; - Did not account for key confounders: anthropometry at baseline, physical activity, diet quality; - Exposure assessment tool not validated; Exposure data based on previous day only (may not reflect usual intake); Changes in exposure or important coexposures were not balanced across groups OR Exposure data only measured at baseline; Unclear attrition and no information on missing data or non-completers; No preregistered data analysis plan; funding source not reported; Funding:; NR
Hur, 2016^40^; PCS, Korean Child–Adolescent Cohort Study (KoCAS), South Korea; Analytic N=605; Included in meta-analysis: Yes; Participant characteristics at baseline: Korean children; - Age: 9.9 (0.3)y; - Female: 48%; - Race/ethnicity: NR; - SEP: 10^4 Korean won/month: 20% ≤300; 41% 301-500; 39% >500; - Anthropometry: Overall, mean (SD), n=770:; BMI: 17.7 (2.6); Fat percent: 20.4 (7.0); WC (cm): 59.6 (7.4); Boys, mean (SD), n=398:; BMI: 18.1 (2.7); Fat percent: 19.8 (7.6); WC (cm): 61.1 (7.7); Girls, mean (SD), n=372:; BMI: 21.0 (6.2) 17.1 (2.4); versus. boys: p<0.0001; Fat percent: 19.8 (7.6) 21.0 (6.2); versus. boys: p=0.02; WC (cm): 58.0 (6.6); versus. boys: p<0.0001; - Physical activity: Overall: 49% <3 hours/wk; 51% ≥3 hours/wk; Boys: 36% <3 hours/wk; 64% ≥3 hours/wk;; Girls: 62% < 3 hours/wk; 38% ≥3 hours/wk;; versus boys: p<0.001; - Diet quality: NR; - TEI: Median (IQR): 1670 (1431, 1936) kcal/d; - Study beverage intake at baseline: Beverage sugar, median (IQR): 0.4 (0.2, 2.4) g/d; Excluded from Study or Analysis: Missing data on age, anthropometric measurements, sugar intake | Exposure: Beverage sugar sources defined as fruit juice, fruit and vegetable drinks, carbonated beverages, sports drinks, coffee, sweet tea, soy milk, energy drinks, and other beverages; Comparator: Continuous intake, g/d; Exposure Assessment Methods and Timing:; Modified 3d diet record, completed with parental assistance. Sugar content of foods and beverages determined from several sources (e.g., KHANES, USDA) and classified into subgroups by source. Baseline (2008); Outcomes and Assessment Methods:; - Height and WC measured by study staff using standard methods; weight and body fat assessed by BIA, BMI calculated from height and weight and age- and gender-specific BMI percentiles and z-scores were calculated using 2007 Korean National Growth Charts; - Baseline, 4y | [underlined: BMI z-score at 4y follow-up], β (SE), kg/m2, multiple linear regression; Overall (n=605): −0.02 (0.03), p=NS; Girls: −0.01 (0.04), p=NS; Boys: −0.04 (0.04), p=NS; [underlined: Fat percent at 4y follow-up], β (SE), multiple linear regression; Overall (n=605): 0.02 (0.21), p=NS; Girls: 0.12 (0.23), p=NS; Boys: −0.08 (0.35), p=NS; [underlined: WC at 4y follow-up], β (SE), cm, multiple linear regression; Overall: −0.07 (0.25), p=NS | Model Adjustments:; - TEI: yes; - Key confounders: sex, age, socioeconomic position (household income); - Other:; Limitations:; - Did not account for key confounders: race and/or ethnicity, anthropometry at baseline, physical activity, diet quality; - Start of follow-up and exposure do not coincide; Exposure not well defined; Exposure data only measured at baseline; High attrition/missing data or no information on non-completers; No preregistered data analysis plan; Risk of bias from selection of the reported result.; Funding:; Ministry of Food and Drug Safety
Hwang, 2020^41^; PCS, National Health Information Database (NHID), South Korea; Analytic N=12,777-14,351, depending on analysis; Included in meta-analysis: No; Participant characteristics at baseline:; Children; - Age: Median age at first included exposure assessment: 33mo; - Female: 49%; - Race/ethnicity: NR; - SEP: NR; - Anthropometry: Mean BMI at 33mo: 16.0 kg/m2; - Physical activity: NR; - Diet quality: NR; - TEI: NR; - Study beverage intake at baseline: 94% consumed <200 cc/d (~6.7oz) at 33mo; Excluded from Study or Analysis: born before January 2008 or after December 2012; born outside South Korea; birth weight <0.5kg or >5.0kg; growth not aligned with birth weight <Weight-I <Weight-II < Weight-III < Weight-IV < Weight-V<Weight-VI < Weight-VII < +3 zscore of 69mo; length not aligned with 25 cm < Height-I < Height-II < Height-III < Height-IV < Height-V< Height-VI < HeightVII < +3 z-score of 69mo; < 5 valid Height, Weight, and BMI measurements during 7 health check-ups | Exposure: SSB (assessed in cc per day); no additional description given; Comparator: Categorical intake (<200 cc/d versus. ≥200 cc/d); Exposure Assessment Methods and Timing:; Exams III, IV, and V surveys: variables measured intake of sugar-sweetened beverages (only Exams IV and V survey data eligible for inclusion due to age at assessment); Exam IV: 30-36 mo (median: 33mo); Exam V: 42-48 mo (median: 45mo); Outcomes and Assessment Methods:; - Height and weight measured by clinical staff; BMI calculated from height and weight.; Adiposity Rebound (AR): BMI increase after nadir at ~4-8y.; Very early AR: before 45mo; Early AR: 57mo; Moderate-to-late AR: no AR until 69mo; - Exams IV-VII (Exams I-III ineligible due to age at assessment): median 33, 45, 57, 69mo | [underlined: Adiposity rebound], <200cc/d versus. ≥200 cc/d, multiple logistic regression; 33 mo (n=14,351): Very early AR: 65.3% versus. 65.6%; Early AR: 15.7% versus. 14.8%; Mod-to-Late AR: 19.0% versus. 19.6%; P=0.71 45 mo (n=12,777): Very early AR: 61.4% versus. 62.5%; Early AR: 18.0% versus. 18.0%; Mod-to-Late AR: 20.6% versus. 19.5%; P=0.71 | Model Adjustments:; - TEI: no; - Key confounders: age; - Other: birth weight; Limitations:; - Did not account for key confounders: sex, race and/or ethnicity, socioeconomic position, anthropometry at baseline, physical activity, diet quality; - Exposure not well defined; No information on non-completers; No preregistered data analysis plan; Funding:; Kangdong Sacred Heart Hospital Fund
Jensen, 2013a^42^; PCS, Prospective Cohort Study, BeActive Eat Well (BAEW) and It’s YourMove! (IYM), Australia; Analytic N=1,465 (BAEW: 751, IYM: 714); Included in meta-analysis: Yes; Participant characteristics at baseline:; Primary (BAEW) and secondary (IYM) students selected from the Barwon–South Western Region of Victoria; - Age: BAEW: 8.0 (2.0)y IYM: 14.6 (1.4)y; - Female: BAEW: 50%; IYM: 53%; - Race/ethnicity: NR; - SEP: SES below state-wide median: BAEW: 60.9% IYM: 62.3%; - Anthropometry: BAEW, mean BMI z-score (SD): 0.8 (1.0)y; Overweight/obesity (IOTF): 24.9%; IYM, mean (SD): 0.5 (1.0)y;; Overweight/obesity (IOTF): 22.7%; - Physical activity: NR; - Diet quality: NR; - TEI: NR; - Study beverage intake at baseline: Median (IQR) sweet drink intake (mL/d) BAEW: 375 (250, 750) IYM: 500 (150, 900); Excluded from Study or Analysis: not in comparison groups of BAEW or IYM; missing information on height, weight, beverage intake, or SES at either time; outliers based on weight and/or height; Children aged 12–13 years from BAEW excluded to ensure no overlap of age groups between the two studies | Exposure: Sweet drink consumption (non-diet soft drinks, fruit juice (including 100% juice), and cordials); number of cans and glasses were converted to mL; Comparator: Continuous intake, 100 mL/d;; Categorical intake, based on change from baseline to follow-up:; No change (ref); Intake decreased; Intake increased; Exposure Assessment Methods and Timing:; Questionnaire (different for each cohort) based on previous day’s or last school day’s intake; not validated; Baseline, 2.1y (BAEW) or 2.3y (IYM) follow-up; Outcomes and Assessment Methods:; - Weight and height measured by trained researchers. BMI calculated. BMI z-score calculated using WHO Growth Standard and Growth Reference; - Baseline, 2.1y (BAEW) or 2.3y (IYM) follow-up | [underlined: BMI z-score at 2y follow-up with sweet drink][underlined: intake at baseline], β (95% CI), multiple linear regression; BAEW: 0.005 (−0.003, 0.012), P=0.18; IYM: 0.004 (−0.002, 0.01), P=0.15; [underlined: BMI z-score at 2y follow-up with 2y change][underlined: in sweet drink intake], β (95% CI), multiple linear regression; BAEW, SES below median (n=457): No change: (ref); Intake decreased: −0.013 (−0.110, 0.084), P=0.78; Intake increased: −0.048 (−0.181, 0.085), P=0.45; BAEW, SES above median (n=294): No change: (ref); Intake decreased: 0.096 (−0.123, 0.314), P=0.36; Intake increased: 0.128 (0.003, 0.253), P=0.05; [Note: Children from lower and higher SES families had similar BMIz scores at T1, but children from higher SES families had a lower intake of sweet drinks at T1 than children from lower SES families (median lower SES: 500 mL, median higher SES: 250 mL, P < 0.0001).]; IYM:; No change: (ref); Intake decreased: −0.078 (−0.188, 0.033), P=0.14; Intake increased: −0.027 (−0.123, 0.070), P=0.52 | Model Adjustments:; - TEI: no; - Key confounders: sex, age, socioeconomic position (SES below state-wide median), anthropometry at baseline; - Other: school cluster, duration between measurements; Limitations:; - Did not account for key confounders: race and/or ethnicity, physical activity, diet quality; - Exposure assessment tool not validated; Exposure includes 100% juice and only assessed previous 24hr; ‘usual intake’ was assessed but only analyzed in supplemental material; Did not report full results for sweet drink types; High attrition/missing data; No preregistered data analysis plan; Funding:; IYM: Victorian Department of Health, National Health and Medical Research Council, Health Research Council (New Zealand), Wellcome Trust (UK), AusAID; BAEW: Commonwealth Department of Health and Ageing, Victorian Department of Human Services, Victorian Health Promotion Foundation (VicHealth)
Jensen, 2013b^43^; PCS, Copenhagen School Child; Intervention Study (CoSCIS), Denmark; Analytic N=269; Included in meta-analysis: Yes; Participant characteristics at baseline:; children; - Age: 6.7 (0.3)y; - Female: 51%; - Race/ethnicity: NR; - SEP: Maternal Education: Elementary: 28%; High school/short ed: 38%; College: 35%; - Anthropometry: BMI ~16 kg/m^2^; - Physical activity: 731 counts/min on accelerometer; - Diet quality: 14 (2.0)% energy from protein, 35.8 (4.6)% of energy from fat; - TEI: 1984 (382) kcal/d; - Study beverage intake at baseline: median intake (g/d): Sweet drinks: 383, Soft drink: 114, Squash: 143; Excluded from Study or Analysis: missing data | Exposure: “Sweet drinks” (soft drink, squash, fruit juice, chocolate milk and drinkable yoghurt) SSB (soft drink and squash only) Artificially sweetened (i.e., light or non-caloric) beverages were not included (100 mL = 100g = 3.38 US fl oz); Comparator: Continuous intake; Exposure Assessment Methods and Timing:; 7d pre-printed food record completed by parents; not validated; At baseline (6yo), 3y follow-up (9yo); Outcomes and Assessment Methods:; - Weight and height measured by trained researchers and used to calculate BMI. Skin-fold thickness was measured at 4 points on non-dominant side of body (triceps, biceps, subscapular, supra iliac) and used to calculate sum of four skinfolds (Σ4SF); - At baseline (6yo), 3y and 7y follow-up (9yo, 13yo) | [underlined: Change in Σ4SF] (mm), β (95% CI); Change in Σ4SF from 6–9y by intake at 6y (n=366):; Sweet drinks: −0.0030 (−0.0129, 0.0068), P=0.53; SSBs: −0.0034 (−0.0138, 0.0071), P=0.50; Soft drinks: −0.0069 (−0.0294, 0.0157), P=0.53; Change in Σ4SF change from 6–13y by intake at 6y (n=286):; Sweet drinks: −0.0024 (−0.0136, 0.0088), P=0.65; SSBs: −0.0043 (−0.0187, 0.0101), P=0.54; Soft drinks: −0.0040 (−0.0381, 0.0301), P=0.81; Change in Σ4SF from 9–13y by intake at 9y (n=269):; Sweet drinks: 0.0140 (−0.0009, 0.0290), P=0.06; SSBs: 0.0176 (−0.0078, 0.0430), P=0.16 Soft drinks:; Comparison grp: −0.0441 (−0.0971, 0.0090), P=0.09; Intervention grp: 0.0871 (0.0480, 0.1263), P=0.001; Change in Σ4SF change from 9–13y by change in intake from 6–9y (n=235):; Sweet drinks: 0.0162 (−0.0020, 0.0343), P=0.08; SSBs: 0.0206 (−0.0075, 0.0486), P=0.14; Soft drinks: 0.0414 (−0.0097, 0.0924), P=0.11; [underlined: Change in BMI] (kg/m2), Linear regression, β (95% CI); Change in BMI from 6–9y by intake at 6y (n=366):; Sweet drinks: −0.0140 (−0.0628, 0.0349), P=0.55; SSB: −0.0051 (−0.0591, 0.0489), P=0.84; Soft drinks: −0.0338 (−0.1299, 0.0623),Pp=0.47; Change in BMI from 6–13y by intake at 6y (n=286):; Sweet drinks: −0.0492 (−0.1228, 0.0244), P=0.18; SSB: −0.0592 (−0.1453, 0.0270), P=0.17; Soft drinks: −0.0353 (−0.2178, 0.1473), P=0.69; Change in BMI from 9–13y by intake at 9y (n=269):; Sweet drinks: 0.0357 (−0.0171, 0.0884), P=0.17; SSB: 0.0078 (−0.0976, 0.1131), P=0.88; Soft drinks: 0.1090 (−0.1261, 0.3442), P=0.34; Change in BMI from 9–13y by change in intake from 6–9y (n=235):; Sweet drinks: 0.0359 (−0.0391, 0.1109), P=0.33; SSB: 0.0260 (−0.0747, 0.1266), P=0.59; Soft drinks: 0.1045 (−0.1292, 0.3382), P=0.36 | Model Adjustments:; - TEI: yes and no; TEI-adjusted data available in paper for some supplemental analyses only. Overall, the relationship between overall sweet drink at 9y and change in sum of 9–13y was the only impacted relationship; - Key confounders: sex, age, socioeconomic position, anthropometry at baseline, physical activity; - Other: maternal BMI; cluster effect by school; intervention/comparison status; Limitations:; - Did not account for key confounders: race and/or ethnicity, diet quality; - Exposure assessment tool not validated; High attrition and no information on non-completers; No preregistered data analysis plan; Funding:; Tryg Foundation; Centre for Intervention Research in Health Promotion and Disease Prevention; The Danish Heart Foundation; ‘Familien Hede Nielsen’ Foundation; University of Southern Denmark
Johnson, 2007^45^; PCS, Avon Longitudinal Study of Parents and Children (ALSPAC), Children in Focus (CIF) subsample, UK; Analytic N=5y exposure & 9y outcome (n=362); 7y exposure & 9y outcome (n=471); Included in meta-analysis: No; Participant characteristics at baseline:; British children born to ALSPAC participants from 04/1991–12/1992.; - Age: 5.16 (0.05)y; - Female: NR; - Race/ethnicity: NR; - SEP: Maternal education and paternal class: Data NR; - Anthropometry: Fat mass at 5y, kg, Mean(SD); 8.47(4.98); Weight at 5y, kg, Mean(SD); 19.52 (2.54); Overweight at 5y (≥95th percentile): 15%; - Physical activity: NR; - Diet quality: Dietary energy density, kJ/g at 5y: 8.52 (1.49); - TEI: TEI at 5y, Mean (SD); 6218 (1393) kJ/d; Misreporting of TEI, TEI / Estimated energy requirement (EER) at 5y, Mean (SD): 1.06 (0.24); - Study beverage intake at baseline: SSB intake Median (IQR); 5y: 57 (0–163) g/d;; 7y: 67 (0–196) g/d; Percent of participants consuming SSB at; 5y: 33%; at 7y: 38%; Paper contains beverage intake data at 5y and 7y stratified by maternal education; Excluded from Study or Analysis: Missing data on diet, body composition, or key confounders | Exposure: SSB intake (fruit squashes, cordials and fizzy drinks with added sugar), measured by volume (g/d) and servings/d (1 serving = 180g); Comparator: Different intake level of SSB (continuous, g/d or svg/d); Exposure Assessment Methods and Timing:; Parent-report, 3-day unweighed dietary records, previously validated using weighed dietary records 5y, 7y; Outcomes and Assessment Methods:; - Fat mass (kg): DXA; Fat mass index (FMI): Fat mass (kg) /; Height (m^5.8); log transformed; Height: valid measure by study staff; Weight: valid measure by study staff; - Age: 9.8 (0.15)y | [underlined: Change in fat mass], kg/serving (95% CI), p-value, Linear regression; Change 5y-9y per serving of SSB at 5y (n=362):; −0.15 (−0.54, 0.24), p=0.45; Change 7y-9y per serving of SSB at 7y (n=471):; −0.11 (−0.37, 0.15), p=0.41; [underlined: FMI quintile], Spearman correlation coefficient By mean volume of SSB consumed (g/d) at age 5y:; −0.06, NS; By mean volume of SSB consumed (g/d) at age 7y:; −0.03, NS | Model Adjustments:; - TEI: yes; - Key confounders: Sex, age, socioeconomic position (maternal education, paternal class), anthropometry at baseline, physical activity, diet quality; - Other: TV watching, parental BMI, fat intake, fiber intake, EI/EER; Limitations:; - Did not account for key confounders: Race and/or ethnicity; - High attrition/missing data; No information on non-completers; No preregistered data analysis plan; Funding:; U.K. Medical Research Council, the Wellcome Trust, and the University of Bristol
Johnson, 2012^44^; PCS, Be Active Eat Well (BAEW), Australia; Analytic N=1,812; Included in meta-analysis: Yes; Participant characteristics at baseline:; Children; - Age: ~8y; - Female: 52%; - Race/ethnicity: NR; - SEP: mother didn’t complete HS ~45%; - Anthropometry: BMI: 17.8 kg/m^2^; BMI z-score ~0.60; - Physical activity: outside play ~1.25h/d; - Diet quality: Mean intake, svg/d; Fruit: 1.9; Vegetables: 1.8; Fast food: 0.17; - TEI: NR; - Study beverage intake at baseline: Sweet drink: mean ~2 svg/d; Excluded from Study or Analysis: Missing data | Exposure: Sweet drinks (1 svg=250 mL of soft drink, 100% fruit juice, diluted fruit juices or cordials, including energy containing flavored mineral water and sports drinks); Comparator: Continuous intake; Exposure Assessment Methods and Timing:; Computer-assisted telephone interview from parents/guardians; from previous day intake; not validated; Baseline, ~2.5y; Outcomes and Assessment Methods:; - Weight and height measured by trained researchers; BMI z-score derived using the zanthro function in Stata against the US CDC 2000 reference population; - Baseline, 2.5y | [underlined: Change in BMI z-score, by change in sweet][underlined: drink consumption], multilevel model, β (95% CI); 0.015 (0.00, 0.03), P=0.02 | Model Adjustments:; - TEI: no; - Key confounders: sex, age, socioeconomic position (maternal education), anthropometry at baseline; - Other: Intervention group; Limitations:; - Did not account for key confounders: race and/or ethnicity, physical activity, diet quality; - Exposure not well defined (includes 100% juice); Exposure assessment tool not validated and only represents previous day, not habitual intake; High attrition/missing data or no information on non-completers; No preregistered data analysis plan; Follow-up time varied substantially across participants (original intervention versus. control group); Funding:; Commonwealth Department of Health and Ageing; Victorian Department of Human Services and the Victorian Health Promotion Foundation (VicHealth); VicHealth Public Health Research Fellowship and the Jack Brockhoff Child Health and Wellbeing Program
Kral, 2008^47^; PCS, U.S.; Analytic N=49; Included in meta-analysis: No; Participant characteristics at baseline:; Children; - Age: ~3y; - Female: 44%; - Race/ethnicity: White: 100%; - SEP: NR; - Anthropometry: BMI z-score, Mean ~ −0.4; WC, Mean ~49.8 cm; - Physical activity: NR; - Diet quality: NR; - TEI: NR; - Study beverage intake at baseline: SSB (oz/d), Mean (SEM); Fruit drinks; Low risk: 0.95 (0.8); High risk: 1.4 (0.9); Soda; Low risk: 0.9 (0.5); High risk: 0.9 (0.6); Soft drinks; Low risk: 1.8 (1.0); High risk: 2.3 (1.0); Soft drinks and fruit juice; Low risk: 6.4 (1.5); High risk: 14.5 (1.5); Excluded from Study or Analysis: not at either high or low risk of obesity based on maternal prepregnancy BMI; missing food records at ages 3, 4, 5, or 6y | Exposure: Fruit drinks including fruit punches, sports drinks, lemonade, instant and iced tea; soda including carbonated caloric beverages; soft drinks including soda, diet soda, and fruit drinks; soft drinks and fruit juice including soda, diet soda, fruit drinks, and fruit juice; Comparator: Continuous intake; Exposure Assessment Methods and Timing:; Three day weighed food and beverage record (2 weekdays, 1 weekend day) recorded by primary caregiver; Represents usual intake; Baseline, 1y & 2y follow ups; Outcomes and Assessment Methods:; - Waist circumference measured in triplicate at the narrowest part of torso by trained anthropometrists; Height and weight measured in triplicate by trained anthropometrists; BMI z-score calculated using CDC growth charts; - Baseline, 1y, 2y, & 3y follow ups | [underlined: WC change from 5y – 6y, per change in soda][underlined: kcal/d from 3y – 5y], β (SE), Linear mixed model; Outliers Excluded from Study or Analysis: 0.04 (0.009), p=0.001; Inclusion of outliers did not change significance; Data NR for fruit drinks, soft drinks, or soft drinks+fruit juice; [underlined: BMI z-score change from 5y – 6y, per][underlined: change in kcal/d from 3y – 5y], β (SE), Linear mixed model; Data NR, p>0.10 | Model Adjustments:; - TEI: yes; - Key confounders: Sex, age, race and/or ethnicity, anthropometry at baseline; - Other: change in BMI z-score or waist circumference from ages 3 to 5 years; Limitations:; - Did not account for key confounders: socioeconomic position, physical activity, diet quality; - Baseline n NR and no information on non-completers; No preregistered data analysis plan; Exposure data based on parental weighed food records; Funding:; NIH; General Clinical Research Center; Nutrition Center of the Children’s Hospital of Philadelphia
Kuhl, 2014^48^; PCS − secondary analysis of trial data, U.S.; Analytic N=36; Included in meta-analysis: Yes; Participant characteristics at baseline:; Preschool children with obesity participating in a weight control intervention; - Age: 56 (12)mo; - Female: 58%; - Race/ethnicity: White: 86%; - SEP: 78% middle-upper class (Hollingshead score >4.0); - Anthropometry: NR; - Physical activity: Moderate and vigorous physical activity, mean (SD): 82 (32) min/d TV viewing, mean (SD): 155 (85) min/d; - Diet quality: Fruit and vegetable intake, svg/d: 3.26; Sweet/salty snacks, svg/d: 3.85; - TEI: Mean (SD): 1437 (290) kcal/d; - Study beverage intake at baseline: mean (SD): 5.08 (4.51) fl oz/d; Excluded from Study or Analysis: <2y or >5y; <95^th^ BMI and >100% over ideal weight; no parent with BMI >25 kg/m2; non-English speaking, living >50 miles from the medical center, having a disability or illness that would interfere with moderate physical activity, taking medication or diagnosed with a condition associated with weight gain, or enrolled in another weight management program; incomplete dietary intake, anthropometric, or activity data | Exposure: All families were instructed to decrease or eliminate SSB for their preschoolers; Treatment groups were collapsed for these analyses, but the original intervention consisted of 3 groups: 1) one-time pediatrician education visit, 2) 18-session behavior and nutrition education program (group & individualized home sessions), and 3) 10-session behavior and nutrition education program (group only); Comparator: Continuous intake; change in SSB intake (fl oz); Outcomes and Assessment Methods:; - Standard anthropometric procedures used to collect height and weight; CDC growth curves used to calculate child z-BMI; - Baseline, 6 months | [underlined: Change in BMI z-score over 6mo], β (95% CI), linear regression; Change in SSB intake over 6mo: 0.191 (−0.011, 0.04), P=NS | Model Adjustments:; - TEI: yes; - Key confounders: sex, age, anthropometry at baseline, physical activity, diet quality (fruit and vegetable intake, sweet/salty snack intake); - Other: television use; Limitations:; - Did not account for key confounders: race and/or ethnicity, socioeconomic position; - No adjustment for original treatment group and no information on between-group differences from trial; high attrition (40%); No preregistered data analysis plan; Funding:; National Institutes of Health
Kunaratnam, 2020^49^; PCS, Secondary analysis of Healthy Beginnings Trial (HBT), Australia; Analytic N=327; Included in meta-analysis: Yes; Participant characteristics at baseline:; Australian children; - Age: 2 (0.04)y; - Female: 50%; - Race/ethnicity: NR; - SEP: Mother’s education: 13.2% high school, 56% technical and further education/diploma, 30.5% university; Mother’s income, AUD$: 21.1% <$40,000, 31.4% $40,000 to <80,000, 47.5% ≥$80,000; Mother’s employment: 17.3% unemployed, 64.8% employed, 17.9% other; Mother’s marital status: 93.8% married/de facto, 6.2% single/divorced/widowed; - Anthropometry: 85.9% without overweight, 10.4% with overweight, 3.7% with obesity; - Physical activity: Outdoor playtime, Mean (SD): 2.22 (1.21) hr/d; - Diet quality: Daily svgs (Mean): Fruit 2.16, Vegetables 1.84, Salty Snacks 0.70, Sweet Snacks 4.08; - TEI: NR; - Study beverage intake at baseline: Cups (250 mL)/d, Mean (SD):; Soft drinks: 0.18 (0.60); Sugary drinks: 0.98 (1.11); Fruit juice: 0.81 (0.91); Excluded from Study or Analysis: mothers age <16y; non-English-speaking mothers; <26wk or >36wk gestation at recruitment; women with severe medical conditions based on advice given by their doctors; inability to provide informed consent; those with known major fetal anomalies; presence of physical or intellectual disability in a child which is likely to influence physical activity or food habits; presence of chronic health problem in a child likely to influence weight or height; inability of parents or carers to communicate in English; missing dietary and lifestyle data at any time point (2, 3.5, or 5y) | Exposure: Soft drinks, sugary drinks (including cordials and sports drinks such as lemonade or Gatorade), fruit juices (not specified as 100% juice); Comparator: Different intake of SSB (continuous, cups/d); Exposure Assessment Methods and Timing:; Semi-quantitative 17-item FFQ validated for use with preschoolers; mothers were asked to report their child’s quantity of cups of soft drinks/cordials/sport drinks and juice (250 mL/cup); At 2y, 3.5y and 5y; Outcomes and Assessment Methods:; - Height and weight: valid measure by study staff; BMI: calculated from weight and height.; BMI categories defined as “healthy weight” or “with overweight/obesity” using IOTF age- and sex-specific BMI cutoffs.; - Baseline and annually thereafter (mean follow-up 4.8y) | [underlined: Incidence of overweight/obesity], β (95% CI), logistic regression; At 3.5y based on soft drink intake at 2y: NS (data not shown); At 3.5y based on sugary drinks intake at 2y: NS (data not shown); At 3.5y based on fruit juice intake at 2y: NS (data not shown); At 5y based on soft drink intake at 3.5y: NS (data not shown); At 5y based on sugary drinks intake at 3.5y: NS (data not shown); At 5y based on fruit juice intake at 3.5y: NS (data not shown); [underlined: Risk of overweight/obesity at 3.5y by SSB intake at 2y], β (95% CI), univariate analysis; β=-0.76; Exp (β) (95%CI): 0.47 (0.20, 1.12), p=0.09 | Model Adjustments:; - TEI: no; - Key confounders: sex, age, socioeconomic position (maternal employment, maternal marital status), anthropometry at baseline, diet quality (intake of fast food, water, milk, vegetable, sweet snacks, breakfast); - Other: maternal age, maternal BMI, screen time, child eating dinner in front of television; Limitations:; - Did not account for key confounders: race and/or ethnicity, physical activity; - Single measure of exposure used in analysis; High and differential attrition/missing data; No preregistered data analysis plan; Limited generalizability; Funding:; Australian National Health and Medical Research Council
Larson, 2018^50^; PCS, Project EAT (Eating and Activity in Teens and Young Adults), U.S.; Analytic N=1120 (adolescence to adulthood); 695 (adulthood); Included in meta-analysis: No; Participant characteristics at baseline:; adolescents without overweight or obesity during transition to adulthood; - Age: 14.9 (1.7)y at Time 1; - Female: 54%; - Race/ethnicity: 50% White; 17% African American, ; 20% Asian; 3% Native American, 5% mixed or other ethnicity/race; 5% Hispanic; - SEP: NR; - Anthropometry: NR; - Physical activity: NR; - Diet quality: NR; - TEI: NR; - Study beverage intake at baseline: NR; Excluded from Study or Analysis: those without height and weight data at ≥1 timepoint; with overweight or obesity at Time 1; women who were pregnant when they reported their adult weight at Time 3 or 4; adults with BMI <18.5 kg/m2 at Time 4 | Exposure: Sugary drinks (carbonated beverages with and without caffeine, and other sugared beverages including fruit drinks, sports drinks, and ice teas); Comparator: Continuous (svg/d); Exposure Assessment Methods and Timing:; Validated FFQ; At baseline (Time 1, 1998–1999), 10y; follow-up, (Time 3, 2008–2009), and 17y; follow-up (Time 4, 2015–2016); Outcomes and Assessment Methods:; - Weight and height were self-reported and used to calculate BMI. Healthy weight status (i.e., non-overweight BMI) was defined using screening guidelines: BMI <85%tile for sex and age at Time 1 and BMI <25 kg/m2 at Time 3 and Time 4. Healthy weight maintenance from adolescence to young adulthood was defined by a non-overweight BMI at Time 1, Time 3, and Time 4.; Healthy weight maintenance in early adulthood was defined by a non-overweight BMI; - At baseline (Time 1, 1998–1999), 10y follow-up, (Time 3, 2008–2009), and 17y follow-up (Time 4, 2015–2016) | [underlined: Healthy weight maintenance at Time 4], OR (95% CI), logistic regression; By sugary drink intake at Time 1; Women (n=602): 0.73 (0.58, 0.91); Men (n=518): 0.80 (0.64, 1.00); By change sugary drink intake from Time 1 to Time 4; Women: 0.57 (0.38, 0.86); Men: 0.82 (0.60, 1.12) | Model Adjustments:; - TEI: yes; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position, anthropometry at baseline (BMI); - Other: none; Limitations:; - Did not account for key confounders: physical activity, diet quality; - High attrition; Weight and height were self-reported; No preregistered data analysis plan; Funding:; NHLBI
Laska, 2012^51^; PCS, Identifying Determinants of Eating and Activity (IDEA) and Etiology of Childhood Obesity (ECHO), U.S.; Analytic N=535; Included in meta-analysis: Yes; Participant characteristics at baseline:; Adolescents; - Age: 14.6y; - Female: 51%; - Race/ethnicity: ~85% white; - SEP: ~75% Parent college graduate ; ~11% Eligible for free/reduced lunch; - Anthropometry: Mean BMI: 22.0 kg/m2; - Physical activity: Mean: ~310 min/d; - Diet quality: Mean (SD); Fast food, purchases/wk: Males: 0.91 (0.88); Females: 0.94 (1.2); Breakfast meals, days/wk: Males: 0.91 (0.2); Females: 0.88 (0.22); - TEI: Mean: 1982 kcal/d; - Study beverage intake at baseline: Svg/d, Mean (SD): Males: 1.02 (1.01); Females: 0.7 (0.84); Excluded from Study or Analysis: <6^th^ or >11^th^ grade at baseline; data available from <2 time points; < 1 day of accelerometry data; < 2d dietary recall data at baseline | Exposure: sweetened soft drinks, fruit drinks, tea, coffee, and/or coffee substitutes; Comparator: continuous intake (svg/d); Exposure Assessment Methods and Timing:; Three 24hr recalls (self-report via telephone); represents 2 weekdays and 1 weekend day; Baseline, 2y; Outcomes and Assessment Methods:; - Height measured without shoes using Shorr Height Board to nearest 0.1 cm; Weight (to nearest 0.1 kg) and percent body fat assessed using digital bioelectrical impedance scale; - Baseline, 2y | [underlined: % body fat, Change per svg/d increase of] [underlined: SSB], Linear regression, β (SE); Males; TEI unadj: 0.51 (0.22), P=0.018; TEI adj: 0.73 (0.21), P=0.001; (Note: the (unadjusted for TEI) finding with %BF was significant at p<0.05 but was not significant at the p-value cutoff used to adjust for multiple comparisons (p<0.003)).; Females; TEI unadj: −0.06 (0.33), P=0.861; TEI adj: 0.04 (0.35), P=0.908; [underlined: BMI, kg/m2, Change per svg/d increase of][underlined: SSB], Random coefficients model/mixed model, β (SE); Males; TEI unadj: 0.25 (0.10), P=0.012; TEI adj: 0.27 (0.10), P=0.008; (Note: these findings with BMI were significant at p<0.05 but was not significant at the p-value cutoff used to adjust for multiple comparisons (p<0.003)); Females; TEI unadj: −0.09 (0.16), P=0.585; TEI adj: −0.05 (0.17), P=0.746 | Model Adjustments:; - TEI: yes and no; - Key confounders: sex, age (grade in school), race and/or ethnicity, socioeconomic position (parent education, qualification for free/reduced price school lunch), anthropometry at baseline, physical activity; - Other: Puberty, study (ECHO versus. IDEA); Limitations:; - Did not account for key confounders: diet quality; - High attrition with no information on non-completers; No preregistered data analysis plan; Funding:; NCI; NHLBI
Laurson, 2008^52^; PCS, U.S.; Analytic N=268; Included in meta-analysis: Yes; Participant characteristics at baseline:; Children; - Age: 11y; - Female: 46%; - Race/ethnicity: NR; - SEP: NR; - Anthropometry: BMI, Mean: ~19.0 kg/m2; Normal weight: 74%; - Physical activity: NR; - Diet quality: NR; - TEI: NR; - Study beverage intake at baseline: Mean (SD), svg/wk; Boys: 6.1 (5.4); Girls: 5.9 (6.2); Excluded from Study or Analysis: incomplete data | Exposure: soda pop, sweetened drinks such as Kool-aid or Gatorade; Comparator: Continuous intake; Exposure Assessment Methods and Timing:; Unvalidated questionnaire, how often they consumed SSB (per week); represents usual intake; Baseline, 18mo follow up; Outcomes and Assessment Methods:; - Height and weight measured using standard procedures; details NR BMI calculated weight in kg divided by height in meters squared; Normal weight (BMI-for-age<85th%);; Without obesity (BMI-for-age<95th%); - Baseline, 18mo follow up | [underlined: BMI, 18-mo change based on baseline SSB][underlined: intake], Linear regression, β (SE):; Boys: Change per svg/wk increase:; Overall sample: 0.114 (0.021), P=0.184; With normal weight: 0.133 (0.022), P=0.219; With normal weight and overweight: 0.061 (0.021), P=0.505; Girls: Change per svg/wk increase:; Overall sample: 0.022 (0.021), P=0.821; With normal weight: 0.004 (0.020), P=0.974; With normal weight and overweight: −0.042 (0.022), P=0.669; [underlined: BMI, 18-mo change based on change in SSB intake], Linear regression, β (SE):; Boys: Change per svg/wk increase:; Overall sample: −0.037 (0.019), P=0.707; With normal weight: −0.052 (0.022), P=0.695; With normal weight and overweight: −0.047 (0.018), P=0.655; Girls: Change per svg/wk increase:; Overall sample: 0.086 (0.027), P=0.405; With normal weight: 0.004 (0.028), P=0.969; With normal weight and overweight: 0.058 (0.028), P=0.578 | Model Adjustments:; - TEI: no; - Key confounders: Sex, age, race and/or ethnicity, anthropometry at baseline; - Other: State of residence (rural Idaho, Montana, or Wyoming); Limitations:; - Did not account for key confounders: SEP, physical activity, diet quality; - Unvalidated exposure measure with high risk of misclassification; No preregistered data analysis plan; Funding:; USDA
Lee, 2015^53^; PCS, National Lung, Heart and Blood Institute’s Growth and Health Study (NGHS), U.S.; Analytic N: Visit 2–3: 1,597, Visit 3–4: 1415, Visit 4–5: 1304, Visit 7–8: 840; Included in meta-analysis: Yes; Participant characteristics at baseline:; girls; - Age: 11.0 (0.57) y; - Female: 100%; - Race/ethnicity: 51% white; 49% Black; - SEP: Parent education: ≤High school 24%, 1–3yr Post High School 38%, College graduate 39%; - Anthropometry: 67% Normal weight, 15% with overweight, 14% with obesity; - Physical activity: 474 (438) – units unclear; - Diet quality: NR; - TEI: 1899 (650) kcal/d; - Study beverage intake at baseline: tsp/d, Mean (SD) ; Liquid added sugar intake: 9.1 (6.8); Excluded from Study or Analysis: Age <9 or >10y; Hispanic ethnicity; racially discordant households | Exposure: Liquid added sugar intake (sum of fructose, glucose, and sucrose added to soft drinks, energy drinks, fruit juices, sweetened milks, and sweetened coffees and teas); 1 tsp = 4g; Comparator: Liquid added sugar intake (continuous; tsp/d); Exposure Assessment Methods and Timing:; 3-d food record; represents dietary intake on two weekdays and one weekend day At Visits 1–5, 7, 8, and 10*; Outcomes and Assessment Methods:; - Height and weight measured twice by research staff in accordance with standard protocols ; BMI calculated as kg/m2. Age- and sex-specific BMI z-scores (BMI z-score) determined using 2000 CDC growth charts; Weight status: Normal (BMI z-score<85th%), with overweight/obesity (BMZ≥85th%); Waist circumference (WC) measured following breath expiration at all visits except Visit 1; - Annually for 10yrs (Visits 1–10*) | [underlined: 1yr ∆ in BMI z-score, Change per 1 tsp][underlined: increase in liquid sugar], Linear regression, β (95% CI); TEI unadj: 0.002 (0.001, 0.003), P=0.003; TEI adj: 0.001 (0.000, 0.002), P=0.10; [underlined: 1yr ∆ in WC, mm, Change per 1 tsp increase in liquid sugar], Linear regression, β (95% CI); Normal weight; TEI unadj: 0.235 (0.108, 0.361), P=0.0003; TEI adj: 0.164 (0.026, 0.303), P=0.02; With overweight/obesity; TEI unadj: 0.280 (0.091, 0.468), P=0.004; TEI adj: 0.207 (0.009, 0.404), P=0.04 | Model Adjustments:; - TEI: yes and no; - Key confounders: sex, age, race/ethnicity, socioeconomic position, anthropometry at baseline, physical activity; - Other: Puberty stage, dieting status, percentage of energy from fat or other carbohydrates; Limitations:; - Did not account for key confounders: diet quality; - No preregistered data analysis plan; Funding:; Children’s Healthcare of Atlanta
Lewis, 2020^56^; PCS, U.S.; Analytic N=14,085; Included in meta-analysis: Yes; Participant characteristics at baseline:; children and adolescents; - Age: <2y: 19%; 2–5y: 23%; 6–11y: 33%; 12–17: 25%; - Female: 50%; - Race/ethnicity: Non-Hispanic white: 35%; Black (African-American): 27%; Other: 8%; Hispanic: 30%; - SEP: NR; - Anthropometry: NR; - Physical activity: NR; - Diet quality: NR; - TEI: NR; - Study beverage intake at baseline: 24% ≤1/wk; 13% several/wk; 22% 1/d; 20% 2/d; 22% >3/day; Excluded from Study or Analysis: Age <6mo or >17y; incomplete exposure or outcome data; dx of pregnancy in year prior or during follow up, children with the highest 1% of health care utilization (>12 in-person medical visits during 1y follow-up); height/weight/BMI/BMIz rate of change measures either below the 1st percentile or above the 99th percentile; no subsequent visits after baseline with height and/or weight data | Exposure: Fruit-flavored drinks, juice from concentrate, punch, KoolAid, soda, sports drinks, sweet tea, flavored milks, 100% fruit juice; Comparator: Categorical intake: “Less than once per week,” “Several per week but not every day,” “1 per day,” “2 per day,” and “3 or more per day.”; Exposure Assessment Methods and Timing:; Standardized screening question about child’s combined fruit juice and SSB consumption (frequency in prior month); adapted from NHANES 2013/14 dietary screener;; Baseline (2017); Outcomes and Assessment Methods:; - Height and weight abstracted from EHR; BMIz calculated from CDC for standards for >2y of age. Converted to BMIz change/y - denominator was the number of days elapsed between measures.; - Baseline (2017); follow-up clinical encounters up to 1y (on same day as dietary data collection when possible); median follow up (25th,75th): 182 days (98,265) | [underlined: BMIz change over 1y, by baseline SSB][underlined: intake,] change in BMI z-score (95% CI), linear mixed-effects models, stratified by age group; 2–5 years at baseline:; <1/d: REF; Several per week: 0.08 (−0.27, 0.43), P>0.05; 1/d: 0.09 (−0.20, 0.38), P>0.05; 2/d: 0.30 (0.-0.002, 0.60), P>0.05; ≥3/d: 0.35 (0.04, 0.65), P<0.01; 6–11 years at baseline:; <1/d: REF; Several per week: 0.11 (−0.04, 0.26), P>0.05; 1/d: 0.16 (0.02, 0.29), P<0.01; 2/d: 0.18 (0.04, 0.32), P<0.01; ≥3/d: 0.18 (0.04, 0.32), P<0.01; 12–17 years at baseline:; <1/d: REF; Several per week: 0.09 (−0.03, 0.21), P>0.05; 1/d: 0.21 (0.10, 0.31), P<0.05; 2/d: 0.17 (0.05, 0.28), P<0.0001; ≥3/d: 0.15 (0.04,0.26), P<0.001 | Model Adjustments:; - TEI: no; - Key confounders: sex, age, race and/or ethnicity, anthropometry at baseline; - Other: Clinic site, encounter type, number of visits, inverse of follow-up time; Limitations:; - Did not account for key confounders: socioeconomic position, physical activity, diet quality; - Exposure not well defined (100% fruit juice and SSB combined); Exposure data only measured at baseline; No preregistered data analysis plan; Funding:; Healthy Eating Research, Robert Wood Johnson Foundation
Libuda, 2008^58^; PCS, Dortmund Nutritional and Longitudinally Designed (DONALD), Germany; Analytic N=244; Included in meta-analysis: Yes; Participant characteristics at baseline:; Children and adolescents; - Age: ~11.9y; - Female: 49%; - Race/ethnicity: NR; - SEP: NR; - Anthropometry: Mean BMI ~18.3 kg/m^2^; Mean percent body fat: ~19%; - Physical activity: NR; - Diet quality: NR; - TEI: ~8200 kJ/d; - Study beverage intake at baseline: Mean (SD); Boys: 277 (296) g/d; Girls: 243 (273) g/d; Excluded from Study or Analysis: missing exposure data (<4 of 6 possible annual dietary records); potential under-reporting of dietary intake (ratio of reported total energy intake and predicted individual BMR above age- and sex-specific cut-off values of 1.04 for boys and 1.01 for girls (6–13 year old subjects) and of 1.07 for boys and 0.97 for girls (14–18 year old subjects) | Exposure: Regular soft drinks (carbonated and uncarbonated sugar-sweetened drinks such as lemonades, iced tea and fruit drinks (diluted and sugar-sweetened fruit juices), sports drinks and energy drinks); Comparator: Continuous intake; MJ/d; Exposure Assessment Methods and Timing:; 3d weighed dietary records; All foods/beverages before consumption and leftovers were weighed and recorded by the parents, or by the older subjects themselves, on 3 consecutive days; participants chose the 1st day of recording within a given period of time; Baseline, annually for 5y; Outcomes and Assessment Methods:; - Body weight measured to nearest 0·1 kg using an electronic scale. Height was measured in a standing position to the nearest 0·1 cm using a digital telescopic stadiometer. Skinfold thickness: Triceps and subscapular skinfolds measured on right side of body using skinfold caliper. Body fat percentage (%BF): sum of both skinfolds using equations of Slaughter. Sex- and age-independent BMI standard deviation scores (BMI-SDS) calculated using German national reference data: Overweight: BMI values 90th – 97th percentile, Obesity: BMI values > 97th percentile; - Baseline, annually for 5y | [underlined: %Body Fat after 5y follow-up by SSB consumption] (MJ), β, repeated measures regression; Boys (n=119); Baseline intake*time: −0.033, P=0.92; Change in intake: 0.046, P=0.87; Girls (n=116); Baseline intake*time: 0.006, P=0.987; Change in intake: 0.450, P=0.186; [underlined: BMI-SDS after 5y follow-up by SSB][underlined: consumption] (MJ), β, repeated measures regression; Boys; Baseline intake*time: 0.037, P=0.211; Change in intake: 0.009, P=0.707; Girls; Baseline intake*time: 0.005, P=0.877; Change in intake: 0.055, P=0.081 | Model Adjustments:; - TEI: yes; - Key confounders: sex, age, socioeconomic position (maternal education level), anthropometry at baseline; - Other: Time in years after maximal growth velocity (equals years of adolescence) as an indicator for pubertal status, birth weight, maternal BMI; Limitations:; - Did not account for key confounders: race and/or ethnicity, physical activity, diet quality; - No preregistered data analysis plan; Funding:; German Federal Ministry of Food, Agriculture and Consumer Protection
Lim, 2009^59^; PCS, Detroit Dental Health Project, U.S.; Analytic N=365; Included in meta-analysis: Yes; Participant characteristics at baseline:; Preschool children; - Age: NR; - Female: 52%; - Race/ethnicity: 100% Black; - SEP: Caregiver education level: <high school: 43.7%, ≥high school: 56.3% ; Caregiver’s annual income: <$10,000: 44.1%, ≥$10,000: 55.9%; - Anthropometry: BMI z-score, mean (SE): 0.14 (0.08); 12.9% with overweight; 10.3% with obesity; - Physical activity: NR; - Diet quality: NR; - TEI: Mean (SE), 2243.3 (81.0) kcal/d; - Study beverage intake at baseline: Baseline intake (oz/d), Mean (SE); Soda: 6.1 (0.5); Fruit drinks: 13.0 (0.7); All SSBs: 19.2 (1.0); Excluded from Study or Analysis: ≤2y at baseline; daily energy intake <750 kcal or >6500 kcal, daily protein intake <19 g, or daily calcium intake >4000 mg | Exposure: SSBs (soda and fruit drinks combined); Soda (excluding diet soda); Fruit drinks (including Kool-Aid, Gatorade, Sunny Delight, Hi-C, Hawaiian Punch, Ocean Spray); Comparator: Continuous intake (oz/d); Categorical, by change in intake: decrease, no change, increase; Exposure Assessment Methods and Timing:; Validated block FFQ; Baseline, 2y follow-up; Outcomes and Assessment Methods:; - Weight measured using calibrated digital scale; Height measured using wall-mounted tape measure. BMI z-score was converted from BMI using 2000 CDC growth charts. Incidence of overweight determined as whether children’s normal weight at baseline became with overweight (85%≤ BMI <95%) or with obesity (BMI ≥95%) at follow-up; - Baseline, 2y follow-up | [underlined: Change in BMI z-score by change in SSB intake] (categorical); Soda: NS, Data NR; Fruit drinks: NS, Data NR; All SSB: NS, Data NR; [underlined: Incidence of overweight among 275 children][underlined: who were normal weight at baseline], OR (95% CI), logistic regression; By baseline beverage intake (oz/d); Soda: 1.04 (0.99, 1.10); Fruit drinks: 1.04 (1.01, 1.07), P<0.05; All SSB: 1.04 (1.01, 1.07), P<0.05; By change in SSB intake (categorical); Soda: NS, Data NR; Fruit drinks: NS, Data NR; All SSB: NS, Data NR; [underlined: Incidence of obesity among 325 children who did not have obesity at baseline] By baseline beverage intake (oz/d); Soda: NS, Data NR; Fruit drinks: NS, Data NR; All SSB: NS, Data NR; By change in SSB intake (categorical); Soda: NS, Data NR; Fruit drinks: NS, Data NR; All SSB: NS, Data NR | Model Adjustments:; - TEI: yes; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position, anthropometry at baseline; - Other: Caregiver BMI; Limitations:; - Did not account for key confounders: physical activity, diet quality; - Unclear if sufficiently powered; No preregistered data analysis plan; Funding:; National Institute for Dental and Craniofacial Research; University of Michigan; Delta Dental Fund of Michigan
Lipsky, 2015^60^; PCS, NEXT Generation Health Study, U.S.; Analytic N=2,785; Included in meta-analysis: Yes; Participant characteristics at baseline:; adolescents; - Age: Mean (SE): 16.27 (0.03)y; - Female: 55%; - Race/ethnicity: Non-Hispanic White: 56%; Non-Hispanic Black: 20%; Other: 5%; Hispanic: 19%; - SEP: Parent education: 34% high school or less, 40% some college, 15% Bachelor’s degree, 12% graduate degree; ; 7-point Family Affluence Scale, mean (SE): 5.41 (0.11); - Anthropometry: BMI, mean (SE): 23.74 (0.18) kg/m^2^; 19% overweight, 20% obesity; - Physical activity: Mean (SE): 3.06 (0.11) hr/wk vigorous physical activity; - Diet quality: fruit and vegetables intake, mean (SE): 3.95 (0.16) times/d; - TEI: NR; - Study beverage intake at baseline: Mean (SE): 1.10 (0.06) times/d; Excluded from Study or Analysis: NR | Exposure: Sugar-sweetened soda/pop (soda); Comparator: Continuous intake (times/d); Exposure Assessment Methods and Timing:; Question modified from YRBSS and Health Behaviour in School-Aged Children study. Participants were asked “During the past 7 days, how many times did you eat or drink sugar-sweetened soda/pop (soda)?” Responses ranged from never to ≥4 times/d; At baseline (wave 1), and annually until wave 4 (3y follow-up); Outcomes and Assessment Methods:; - Height and weight were self-reported and used to calculate BMI. Sex- and age-specific CDC BMI percentiles used to define baseline weight status.; - At baseline (wave 1), and annually until wave 4 (3y follow-up) | [underlined: Time-varying BMI (kg/m]^2^[underlined: ) by time-varying] [underlined: SSB intake (times/d) over 3y follow-up], β (SE), linear generalized estimating equations − 0.15 (0.12), p=0.23; [underlined: Change in BMI (kg/m]^2^[underlined: ) over 1y by SSB][underlined: intake (times/d)], β (SE), linear GEE; Retrospective (current BMI - previous wave BMI): 0.01 (0.04), p=0.72; Prospective (next wave BMI - current BMI): 0.04 (0.04), p=0.38 | Model Adjustments:; - TEI: no; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position (Family Affluence Scale, parent educational attainment), anthropometry at baseline, physical activity; - Other: School urbanicity (urban/suburban/rural); wave; complex sampling design; Limitations:; - Did not account for key confounders: diet quality; - No information on non-completers; height and weight were self-reported; No preregistered data analysis plan; Funding:; NICHD; NHLBI; National Institute on Alcohol Abuse and Alcoholism; Maternal and Child Health Bureau of the Health Resources and Services Administration, National Institute on Drug Abuse
Ludwig, 2001^61^; PCS, Planet Health intervention and evaluation project, U.S.; Analytic N=548; Included in meta-analysis: Yes; Participant characteristics at baseline:; Children and adolescents; - Age: 11.7 (0.8)y; - Female: 48%; - Race/ethnicity: 64% White; 14% Afro-American; 8% Asian; 8% American Indian or other; 15% Hispanic; - SEP: Median household income lower than that for all households in Massachusetts; - Anthropometry: BMI, mean (SD): 20.73 (3.99) kg/m^2^; 27% with obesity; - Physical activity: Activity ≥3.5 MET: 1.34 (1.09) hr/d; 38% Exercised to lose weight; - Diet quality: NR; - TEI: Mean (SD): 8950 (4500) kJ/d; - Study beverage intake at baseline: NR; Excluded from Study or Analysis: not in control group of Planet Health intervention and evaluation project; did not reside in Boston area between 1995–1997; not in grade 6–7 at baseline; changed schools at baseline; enrolled in special education classes; grades other than 6th or 7th; did not complete English-language version of questionnaire; implausible energy intake (≤2090 kJ/d or ≥29,260 kJ/d) | Exposure: soda; Hawaiian punch, lemonade, Koolaid, or other sweetened fruit drink; iced tea (not artificially sweetened).; Comparator: Continuous intake, svg/d; Exposure Assessment Methods and Timing:; Youth food-frequency questionnaire (validated); intake assessed as frequency of consumption over past 30 days. Soda: never or < 1 can/mo, 1–3 cans/mo; 1 can/wk; 2–6 cans/wk; 1 can/d; ≥2 cans/d; sweetened fruit drinks: never or less than one glass per month, 1–3 glasses/mo, 1 glass/week, 2–4 glasses/week, 5–6 glasses/week, 1 glass/d, ≥2/d; iced tea: never or less than one glass/mo, 1–3 glasses/mo, 1–4 glasses/wk, ≥5 glasses/wk); Baseline, 19mo; Outcomes and Assessment Methods:; - Height measured to nearest 0.1 cm using a Shorr stadiometer; Weight measured to nearest 0.1 kg on a portable electronic scale; BMI calculated as kg/m2. Triceps-skinfold thickness measured twice by trained project staff with calibrated Holtain calipers. Obesity defined by a composite indicator of BMI and triceps skinfold thickness ≥85th% of age- and sex-specific reference data; - Baseline, 19mo | [underlined: BMI change], mean (95% CI), linear regression, n=548; By SSB svg/d at baseline:; TEI unadj: 0.13 (0.05–0.21), p=0.03; Adjusting for TEI did not change significance; By increase in SSB svg/d:; TEI unadj: 0.20 (0.09–0.30), p=0.02; Adjusting for TEI did not change significance; [underlined: Obesity incidence], OR (95% CI), logistic regression, n=398; By SSB svg/d at baseline: 1.46 (0.57–3.77), p=0.33; Adjusting for TEI did not change significance; By increase in SSB svg/d: 1.44 (1.22–1.70), p=0.004; Adjusting for TEI did not change significance | Model Adjustments:; - TEI: yes and no; - Key confounders: sex, age, race and/or ethnicity, anthropometry at baseline (BMI and triceps-skinfold thickness), physical activity; - Other: Percent energy from fat, energy-adjusted fruit juice intake, time spent watching television and videos (baseline and change over time) menarcheal status, indicator variables for schools; Limitations:; - Did not account for key confounders: socioeconomic position, diet quality; - No preregistered data analysis plan; Limited statistical power to detect associations with incident obesity (n=37 incident cases); Funding:; NIDDK; NICHD; CDC; Charles H. Hood Foundation
Macintyre, 2018^62^; PCS, Growing Up in Scotland (GUS), Scotland; Analytic N=2,332; Included in meta-analysis: Yes; Participant characteristics at baseline:; Children; - Age: NR; - Female: 49%; - Race/ethnicity: NR; - SEP: Maternal education: 30% standard grades/intermediate vocational; 33% higher grades/upper vocational; 28% degree level academic/vocational qualifications; - Anthropometry: BMI: 74% “Healthy weight”; 16% with overweight; 11% with obesity; - Physical activity: 64% met physical activity guidelines (420 min/wk); - Diet quality: Breakfast consumption: ~95% usually eat breakfast (higher in those with lower LNCSB consumption) Fruit and vegetable consumption: ~70% ate <5 different types of fruits or vegetables in previous day (higher consumption of F/V in those with lower LNCSB consumption) Sweets/crisps consumption: ~45% eat sweets or crisps < every day of the week (lower crisp consumption in those with lower LNCSB consumption) Processed meals consumption: ~23% had processed meal ≥2x in past 7 days (lower processed meal consumption in those with lower LNCSB consumption); - TEI: NR; - Study beverage intake at baseline: Never or <1/wk: 44%; 1–6/wk: 15%; ≥1/d: 41%; Excluded from Study or Analysis: not selected as part of random nationally representative sample of Scottish children; not age 10mo in 2005–2006; cases deemed to be “sensitive” (e.g., because of parental death); respondent not child’s mother (n = 61); missing data on exposure (n = 1)or outcome (n = 71); respondent elected to skip physical activity questions because of child’s longstanding illness or disability (n = 2); outliers on BMI (n = 1) and television viewing (n = 5); cases with no longitudinal weight (who had not responded at every sweep) (n = 69) | Exposure: soft drinks and diluted juice; not including diet or sugar-free drinks, fresh fruit juice, or water; Comparator: Categorical intake: Never or <1/wk (ref), 1–6 times/wk, ≥1/d; Exposure Assessment Methods and Timing:; Parent interview using single question on frequency of intake; Sweep 5 (age 4–5y); Outcomes and Assessment Methods:; - Height and weight measured on non-carpeted surface by GUS project team following a protocol. BMI calculated as kg/m2. BMI classification defined according to British 1990 growth reference curves (Overweight: 85th% cutoff, Obesity: 95th% cutoff); - At Sweep 4: (age 3–4y), and at ~3y follow-up (Sweep 7: age 7–8y) | [underlined: Overweight including Obesity at 7–8y], Logistic regression, OR (95% CI); <1/wk (ref) versus; 1–6 times/wk: 0.94 (0.68, 1.30), P=0.69; ≥1/d: 1.18 (0.92, 1.52), P=0.19; [underlined: Obesity at 7–8y], Logistic regression, OR (95% CI); <1/wk (ref) versus; 1–6 times/wk: 1.65 (1.12, 2.44), P=0.01; ≥1/d: 1.19 (0.85, 1.65), P=0.30; [underlined: BMI], kg/m2, Linear regression, β (95% CI); <1/wk (ref) versus; 1–6 times/wk: 0.06 (−0.17, 0.29), P=0.59; ≥1/d: 0.19 (0.01, 0.37), P=0.04 | Model Adjustments:; - TEI: no; - Key confounders: sex, age, socioeconomic position (maternal education, household income), anthropometry at baseline, physical activity, diet quality (consumption of breakfast, fruit and vegetables, milk, water, sweets/crisps, and processed meals); - Other: Maternal age; mother’s BMI; television viewing on weekdays; Limitations:; - Did not account for key confounders: race and/or ethnicity; - Start of follow-up and exposure do not coincide; Unclear if exposure assessment tool is validated; Exposure data only measured at baseline; High attrition with no information on non-completers; No preregistered data analysis plan; Funding:; Medical Research Council; Chief Scientist Office of the Scottish Government Directorates
Malihi, 2021^64^; PCS, Growing Up in New Zealand (GUiNZ), New Zealand; Analytic N=5,598; Included in meta-analysis: No; Participant characteristics at baseline:; Children; - Age: 2y; - Female: 49%; - Race/ethnicity: European: 52%; Asian: 12%, Māori: 13%, Pacific: 13%; Other ethnicities (MELAA/Other): 10%; - SEP: Maternal education: No secondary school: 6%; Secondary school: 22%; Diploma/trade: 30%; Bachelor degree: 25%; Higher education: 17%; NZDep2006 Index of Deprivation: Low: 29%, Medium: 38%, High: 34%; Income tested benefit receipt: None: 22%; Once: 21%; Twice: 14%; 3x: 16%; 4x: 10%; 5x: 17%; Food security index during infancy: Food secure: 64%; - Anthropometry: NR; - Physical activity: Total screen time: 21% none; 42% ≤1hr/d; 20% 1–2 hr/d; 17% >2 hr/d; - Diet quality: Takeaway food consumption frequency at 2y: 25% none, 44% ≥1/mo, 29% ≥1/wk, 1.5% ≥1/d; - TEI: NR; - Study beverage intake at baseline: Soft drink / fizzy drink consumption frequency: None: 62%; ≥1/mo: 13%; ≥1/wk: 17%; ≥1/d: 7%; Excluded from Study or Analysis: missing data or “do not know”/“do not remember” responses on exposure, confounders, or outcomes; child of multiple pregnancy and not the first born child; age >59.5mo when anthropometric measurements were conducted | Exposure: Soft drink / fizzy drink; Comparator: Categorical intake, consumption frequency (none, ≥1/mo, ≥1/wk, ≥1/wk, ≥1/day); Exposure Assessment Methods and Timing:; - Semiquantitative FFQ assessing previous 4wk; - Baseline (2y); Outcomes and Assessment Methods:; - Weight and height measured by trained interviewers; IOTF cutoff points used to determined obesity; - Age 4.5y | [underlined: Obesity incidence at age 4.5y, by intake at] [underlined: 2y], Poisson regression, RR (95% CI), p-value; None: REF; ≥1/mo: 1.25 (0.94, 1.65); ≥1/wk: 1.25 (0.99, 1.59); ≥1/d: 1.29 (0.94, 1.77), p = 0.19 | Model Adjustments:; - TEI: No; - Key confounders: Sex, age, race and/or ethnicity, SEP (income tested benefit recipient, NZ deprivation index, maternal education); - Other: Maternal age, birth weight, rurality status, early childhood education attendance; Limitations:; - Did not account for key confounders: Anthropometry at baseline (though birth weight was adjusted for), physical activity, diet quality; - Exposure not well defined; Exposure data only measured at baseline; no information on non-completers; No preregistered data analysis plan; Funding:; Cure Kids New Zealand and National Science Challenge; New Zealand Ministries of Social Development, Health, Education, Justice and Pacific Island Affairs; Ministry of Business, Innovation and Employment; Ministry for Women; the Department of Corrections; Social Policy Evaluation and Research Unit; Te Puni Kokiri; New Zealand Police; Sport New Zealand; the Housing New Zealand Corporation; and the former Mental Health Commission, The University of Auckland and Auckland UniServices Limited; the Health Research Council of New Zealand, Statistics New Zealand, the Office of the Children’s Commissioner and the Office of Ethnic Affairs
Marshall, 2018^65^; PCS, Iowa Fluoride and Iowa Bone Development Studies, U.S.; Analytic N=571; Included in meta-analysis: No; Participant characteristics at baseline:; Children; - Age: NR; - Female: 51%; - Race/ethnicity: Non-Hispanic white: 94%; - SEP: Mother had 4y college degree: 45%; Household annual income ≥$60,000: 19%; - Anthropometry: Weight, Mean~20.0 kg; Height, Mean~111.4 cm; - Physical activity: NR; - Diet quality: Mean Adequacy Ratio (average of nutrient adequacy ratios, used to estimate overall diet quality) Males: 0.95; Females: 0.94; - TEI: Median~1360 kcal/d; - Study beverage intake at baseline: Median ~2.7oz/d; Excluded from Study or Analysis: <2 assessments ages 2–8.5y and <1 ages 9–17y; no height measurement at corresponding age at exams during ages 5–17y | Exposure: SSB (no other details provided); Comparator: Continuous intake; 8 oz/d; Exposure Assessment Methods and Timing:; - Validated beverage frequency questionnaire; represents previous week’s beverage intakes; - At 3- to 6-mo intervals: Ages 2–4.7, 5–8.5, 9–10.5, 11–12.5, 13–14.5, and 15–17y Intake averaged across all time points for analysis; Outcomes and Assessment Methods:; - Height measured without shoes using stadiometer during clinic visits; - At ages 5, 9, 11, 13, 15, 17y | [underlined: Height, cm, Change per 8 oz/d increase]; Linear regression; β: 0.15, 95% CI: −0.06, 0.36, P=0.16 | Model Adjustments:; - TEI: yes; - Key confounders: Sex, age, SEP (household income, mother’s educational attainment), anthropometry at baseline, diet quality (mean adequacy ratio, which is an average of each individual’s nutrient adequacy ratio); - Other:; Limitations:; - Did not account for key confounders: Race and/or ethnicity, physical activity; - No information on non-completers; No preregistered data analysis plan; Funding:; NIH; The Roy J. Carver Charitable Trust; Delta Dental of Iowa Foundation
Marshall, 2019^66^; PCS, Iowa Fluoride and Iowa Bone Development Studies, U.S.; Analytic N=623; Included in meta-analysis: Yes; Participant characteristics at baseline:; Children; - Age: NR; - Female: 51%; - Race/ethnicity: Non-Hispanic white: 94%; - SEP: Mother had 4y college degree 45%; Household annual income ≥$60,000 19%; ; Low 25%, Middle 38%, High 38%; - Anthropometry: BMI, Mean~16.0 kg/m2; BMI z-score, Mean~0.31; - Physical activity: NR; - Diet quality: Mean Adequacy Ratio (average of nutrient adequacy ratios, used to estimate overall diet quality) Males: 0.95; Females: 0.94; - TEI: Median~1360 kcal/d; - Study beverage intake at baseline: Median ~2.7oz/d; Excluded from Study or Analysis: <2 assessments ages 2–8.5y and <1 ages 9–17y; no height measurement at corresponding age at exams during ages 5–17y | Exposure: SSB (no other details provided); Comparator: Continuous intake; 8 oz/d; Exposure Assessment Methods and Timing:; - Validated beverage frequency questionnaire; represents previous week’s beverage intakes; - At 3- to 6-mo intervals: ages 2–4.7, 5–8.5, 9–10.5, 11–12.5, 13–14.5, and 15–17y; Outcomes and Assessment Methods:; - Height measured without shoes using stadiometer during clinic visits; Weight was measured at clinic visit using a standard physician’s scale; BMIs were calculated from weight and height measures (kg/m2); Age- and sex-specific BMI z-scores (BMI z-score) calculated 2000 CDC growth charts; - At ages 5, 9, 11, 13, 15, 17y | [underlined: BMI z-score, Change per 8 oz/d increase in SSB], linear regression; β: 0.050, 95% CI: 0.022, 0.079, P=0.001; [underlined: Estimated effect of SSB intake on BMI z-score prior to age 9], linear mixed model; β: 0.076, 95% CI: −0.023, 0.175, P=0.13; [underlined: Estimated effect of SSB intake on BMI z-score after age 9], linear mixed model; β: 0.048, 95% CI: 0.019, 0.077, P=0.001 | Model Adjustments:; - TEI: yes; - Key confounders: Sex, age, SEP (household income, mother’s educational attainment), anthropometry at baseline, diet quality (mean adequacy ratio, which is an average of each individual’s nutrient adequacy ratio); - Other: other beverage intake; Limitations:; - Did not account for key confounders: Race and/or ethnicity, physical activity; - No information on non-completers; No preregistered data analysis plan; Funding:; NIH; The Roy J. Carver Charitable Trust; Delta Dental of Iowa Foundation
Millar, 2014^67^; PCS, Longitudinal Study of Australian Children (LSAC), Australia; Analytic N=4,169; Included in meta-analysis: Yes; Participant characteristics at baseline:; Children; - Age: 4.8 (0.2)y; - Female: 49%; - Race/ethnicity: NR; - SEP: NR; - Anthropometry: mean BMI z-score 0.65 (1.00); - Physical activity: NR; - Diet quality: High fat foods (mean number of times consumed in the 24 hours prior to survey) wave 1:; Males 2.0 (1.3); Females 1.9 (1.2); - TEI: NR; - Study beverage intake at baseline: SSB intake at baseline: 1.7 (1.2) times consumed in previous 24hr; Excluded from Study or Analysis: children not in the K-cohort (4–5y at wave 1-baseline); missing data | Exposure: fruit juice, soft drink, or cordial; not including diet soft drinks or cordials; Comparator: SSB intake (continuous; frequency of consumption per day); Exposure Assessment Methods and Timing:; - Two survey questions (parent-report during face-to-face interview) on frequency of intake in previous 24hr; - At baseline (Wave 1, 2004), and every 2y (Waves 2–4: 2006, 2008, 2010); Outcomes and Assessment Methods:; - Height measured twice to nearest 0.1 cm using portable rigid stadiometer (average used in analysis); Weight measured to nearest 50g using glass bathroom scales; Age- and sex-specific BMI z-scores (BMI z-score) calculated using WHO Growth Standard for 6- to 60-month-old children and Growth Reference for 5- to 19-year-old children; - At baseline (Wave 1, 2004), and every 2y (Waves 2–4: 2006, 2008, 2010) | [underlined: BMI z-score, Multilevel growth model], β (95% CI); Change over 4 waves per each additional occurrence of SSB intake per day: 0.015 (0.004, 0.025), P<0.01; Using imputed maternal BMI data (20 imputations −21% missing before imputation) 0.017 (0.007, 0.027), P≤0.01 | Model Adjustments:; - TEI: no; - Key confounders: sex, age, socioeconomic position (composite household socio-economic position), anthropometry at baseline; - Other: Wave, mother’s BMI, high-fat food intake; Limitations:; - Did not account for key confounders: race and/or ethnicity, physical activity, diet quality; - Exposure data collection tool not validated, Exposure is frequency of SSB, not amount, and only represents 1, 24hr period, which may not represent usual intake, Level of missing data is low but not specified whether it differed by exposure level, No preregistered data analysis plan; Funding:; NR
Mirmiran, 2015^68^; PCS, Tehran Lipid and Glucose Study (TLGS), Iran; Analytic N=327; Included in meta-analysis: Yes; Participant characteristics at baseline:; Children and adolescents; - Age: 13.6 (3.7)y; - Female: 68%; - Race/ethnicity: NR; - SEP: NR; - Anthropometry: BMI ~19.4 kg/m2; - Physical activity: NR; - Diet quality: Meat and processed meat: ~13 g/1000 kcal; Fruit: 130–183 g/1000 kcal; Vegetables: ~100 g/1000 kcal; Dietary fiber: ~14.5 g/1000 kcal; - TEI: ~2559 kcal/d; - Study beverage intake at baseline: mL/d, Mean; SSB intake: Boys, 98; Girls, 70; Fruit juice drink and SSSD intake: NR; Excluded from Study or Analysis: high fasting plasma glucose at baseline; missing data; energy intake to energy requirement ratios beyond ±3SD range | Exposure: SSB intake (sugar sweetened carbonated soft drinks (SSSDs), “did not differentiate between artificial non-caloric sweeteners and those containing caloric sugar e.g. fructose or sucrose”) and combined fruit juice drinks (both 100% fruit juice and sugar sweetened synthetic juice drinks that were not 100% juice)); 1 svg= 1 cup (250 mL); Comparator: SSB intake (categorical; mL/d): Quartile 1 (Median 9.3), Quartile 2 (Median 32.0), Quartile 3 (Median 58.6), Quartile 4 (Median 142.2); Exposure Assessment Methods and Timing:; - Validated semi-quantitative FFQ; represents usual dietary intake during the past year (parent-assisted if needed); - Baseline; Outcomes and Assessment Methods:; - Weight measured to nearest 100 g using digital scale; Height measured in standing position without shoes using stadiometer; BMI calculated as kg/m2. Waist circumference (WC) measured to nearest 0.5 cm at umbilicus using measuring tape. Abdominal obesity: For children and adolescents, WC ≥90th% for age and sex according to national reference curves; for participants >18y, WC ≥91cm for women and ≥89cm for men; - baseline, 3y follow-up (mean=3.6y) | [underlined: Incident abdominal obesity, Change per][underlined: quartile increase], Logistic regression, OR (95% CI); SSB:; Q1 (ref) versus; Q2: 2.16 (0.82, 5.68); Q3: 1.86 (0.71, 4.84); Q4: 3.66 (1.40, 9.59); P for trend: 0.016; Fruit juice drink:; Q1 (ref) versus; Q2: 2.31 (0.95, 5.61); Q3: 0.88 (0.33, 2.35); Q4: 1.26 (0.48, 3.34); P for trend: 0.865; SSSD:; Q1 (ref) versus; Q2: 1.57 (0.60, 4.06); Q3: 2.03 (0.78, 5.28); Q4: 3.78 (1.08, 13.27); P for trend: 0.043 | Model Adjustments:; - TEI: yes; - Key confounders: sex, age, anthropometry at baseline, physical activity, diet quality (red and processed meat, dietary fiber, fruits, vegetables); - Other: family history of diabetes, tea and coffee; Limitations:; - Did not account for key confounders: race and/or ethnicity, socioeconomic position; - Exposure measured at baseline only; Exposure not well defined; No preregistered data analysis plan; Funding:; Research Institute for Endocrine Sciences, Shahid Beheshti University of Medical Sciences, Tehran, Iran
Mrdjenovic, 2003^69^; PCS, Cornell Summer Day Camp (RCT), U.S.; Analytic N=21; Included in meta-analysis: No; Participant characteristics at baseline:; Children and adolescents; - Age: ~8y; - Female: 37%; - Race/ethnicity: mostly white; 17% (n=5) from minority groups; - SEP: mostly upper middle-class families; - Anthropometry: BMI ~16.5 kg/m2; - Physical activity: NR; - Diet quality: NR; - TEI: ~1618 kcal/d; - Study beverage intake at baseline: Mean~120 g/d; Excluded from Study or Analysis: Known food intolerances or allergies; children with poor dietary recording | Exposure: Sweetened drinks (carbonated or noncarbonated fruit-flavored drinks like frozen fruit juices diluted with water, fruit punch, Kool-Aid, and other powdered drinks, less than 100% fruit juice, soda, Snapple, or tea); Comparator: sweetened drink intake (categorical; oz/d): 0 (no drink consumed); <6 (1 svg/d); 6–12 (2 glasses or 1 cup); >12 ; >16; Exposure Assessment Methods and Timing:; - Food consumption at camp (during weekdays) was weighed before and after consumption; food consumption at home (weekend) calculated based on recorded amounts by converting home measures into grams. Children served themselves a drink of their choice whenever they wished, but were requested to report the amounts they drank.; - Daily throughout a 4–8wk follow up; Outcomes and Assessment Methods:; - Height measured without shoes to the nearest cm with a portable field stadiometer; Weight measured to the nearest gram in the morning before breakfast using portable digital scale. BMI calculated from weight and height.; - Baseline, during last week of camp (NR) | [underlined: Weight Gain by SSB intake], kg, multiple regression, β (SD); <6 oz/d: Data NR; 6–16 oz/d: 0.32–0.48 (0.4); >16: 1.12 (0.7); P-trend=0.4 | Model Adjustments:; - TEI: yes; - Key confounders: None; - Other:; Limitations:; - Did not account for key confounders: sex, age, race and/or ethnicity, socioeconomic position, anthropometry at baseline, physical activity, diet quality; - Exposure based on self-report by child; Power analysis NR; Potential selection bias (unclear why 30 of 42 were selected into study); High attrition (30%); Follow-up time NR; Unclear of outcome assessment timing; No preregistered data analysis plan; Funding:; USDA
Muckelbauer, 2016^70^; PCS, Germany; Analytic N=1,987; Included in meta-analysis: Yes; Participant characteristics at baseline:; Children; - Age: 8.3 (0.7) y; - Female: 53%; - Race/ethnicity: 44% migrational background (child or parent born in foreign country); - SEP: NR; - Anthropometry: BMI 17.2 (2.9) kg/m2; 76% with normal weight, 17% with overweight, 7% with obesity; - Physical activity: NR; - Diet quality: NR; - TEI: NR; - Study beverage intake at baseline: glasses/d, Mean (SD); Sugar-containing beverages: 2.7 (2.4); Soft drinks: 1.3 (1.7); Juice: 1.4 (1.7); Excluded from Study or Analysis: not enrolled at randomly selected elementary schools; missing data on exposure and/or outcome | Exposure: SSBs combined intake of soft drinks, including lemonades and iced tea; and juices, including fruit drinks of any percentage fruit juice); 1 glass ~ 200 mL; Comparator: Sugar-containing beverage Continuous; glass/d; Categorical (quintiles):; Q3 (ref): no or small change in beverage consumption; Q5: highest increase in beverage consumption; Exposure Assessment Methods and Timing:; - Semi-quantitative 24-hr recall questionnaire; - At baseline (start of school year), and end of same school year (mean follow up 8.2±0.2 mo); Outcomes and Assessment Methods:; - Height and weight measured in light clothes by trained study staff; - BMI calculated as kg/m2; - Weight categories (normal weight, overweight and obesity) defined according to recommendations of the International Obesity Task Force; - At baseline (start of school year), and end of same school year (mean follow up 8.2±0.2 mo) | [underlined: BMI], kg/m2, Linear regression, β (95% CI); Mean change per glass/d increase:; SSBs: 0.02 (0.00, 0.03), P=0.011; Soft drinks: 0.02 (0.00, 0.04), P=0.019; Juice: 0.01 (−0.01, 0.03), P=0.18; [underlined: BMI], kg/m2, Linear regression, β; Mean change by quintile of beverage intake: Sugar-containing beverages; Q3 (ref) versus:; Q4: 0.03; Q5: 0.16 (0.06, 0.25); P for trend: 0.014; Soft drinks:; Q3 (ref) versus:; Q4: 0.06; Q5: 0.09; P for trend: 0.057; Juice:; Q3 (ref) versus:; Q4: 0.00; Q5: 0.05; P for trend: 0.82; [underlined: Overweight (including Obesity)], Logistic regression, OR (95% CI); SSBs: 0.99 (0.90, 1.09), P=0.83; Soft drinks: 0.99 (0.88, 1.12), P=0.89; Juice: 0.98 (0.86, 1.12), P=0.76; [underlined: Obesity, Logistic regression], OR (95% CI); SSBs: 1.22 (1.04, 1.44), P=0.014; Soft drinks: 1.17 (0.93, 1.48), P=0.19; Juice: 1.29 (1.02, 1.61), P=0.030; When adjusting for baseline prevalence instead of BMI:; SSBs: 1.13 (0.99, 1.30), P=0.064; Soft drinks: 1.16 (0.96, 1.39), P=0.13; Juice: 1.11 (0.93, 1.34), P=0.25 | Model Adjustments:; - TEI: no; - Key confounders: sex, age, race/ethnicity, anthropometry at baseline; - Other: Study arm, follow-up duration, water intake, baseline beverage intake, change in intake of other beverages; Limitations:; - Did not account for key confounders: socioeconomic position, physical activity, diet quality; - Exposure not well defined (multiple beverage types), Exposure data collection tool not validated and only represents previous day, not habitual intake, No preregistered data analysis plan; Funding:; None received
Mundt, 2006^71^; PCS, Pediatric Bone Mineral Accrual Study (PBMAS), Canada; Analytic N=217; Included in meta-analysis: No; Participant characteristics at baseline:; Children; - Age: NR; - Female: 52%; - Race/ethnicity: ~95% White; - SEP: NR; - Anthropometry: NR; - Physical activity: NR; - Diet quality: NR; - TEI: NR; - Study beverage intake at baseline: NR; Excluded from Study or Analysis: children with history of chronic disease or long-term medication use, missing data on physical activity, SSB consumption, body composition, and age | Exposure: SSBs (beverages that contained added sugar such as soft drinks, sport drinks, drinks made from crystals or flavored syrup, punches); Comparator: Continuous intake, oz/d; Exposure Assessment Methods and Timing:; - 24hr recalls, self-reported; yearly averages were calculated; - 3 times per year (for first 3 years), then 2 times/y thereafter. Maximum follow-up: 7y; Median: 5y; Outcomes and Assessment Methods:; - Fat mass and fat-free mass assessed with DEXA; - Annually for 7y (median 5y) | [underlined: Fat mass] (kg), Mean coefficient (SE), multilevel linear modeling (random effects models); Males: −0.0141 (0.00846), P=NS; Females: −0.0188 (0.0118), P=NS | Model Adjustments:; - TEI: yes; - Key confounders: sex, age, anthropometry at baseline; - Other: fat-free mass; Limitations:; - Did not account for key confounders: race and/or ethnicity, socioeconomic position, physical activity, diet quality; - No information on non-completers; No preregistered data analysis plan; Funding:; Canadian National Health and Research Development Program; Canadian Institute of Health Research; Saskatchewan Health Research Foundation
Newby, 2004^72^; PCS, U.S.; Analytic N=1,345; Included in meta-analysis: Yes; Participant characteristics at baseline:; Low-income preschool children; - Age: 2.9 (0.7)Y; - Female: 50%; - Race/ethnicity: White 83%; Native American 11%, Other 6%; - SEP: Maternal education, Mean~12.6y; Poverty level: <100%: 55%; 100–133%: 22%; >133–185%: 23%; - Anthropometry: BMI, Mean~16.6 kg/m2; At risk of overweight 14%, Overweight 6%; - Physical activity: NR; - Diet quality: NR; - TEI: Mean~1747 kcal/d; - Study beverage intake at baseline: Soda intake: Mean~1.2 oz/d; ≥12 oz/d: ~3%; Excluded from Study or Analysis: not seen by North Dakota WIC Program between 1/1/95 and 6/30/98; only 1 clinic visit, underweight (based on age- and sex-specific 5th percentile BMI), implausible energy intake (<800 kcal or >3500 kcal/d), unreasonable measures for weight-for height, weight-for-age or height-for-age, “suspicious” change in BMI between visits (< −4 or >4 kg/m2), child breastfeeding at baseline | Exposure: Fruit drinks (e.g., lemonade, fruit punch), non-diet soda; Comparator: Continuous intake, oz/d; Exposure Assessment Methods and Timing:; - Validated FFQ; represents dietary intake during previous month; - At baseline, follow-up 6–12mo later (mean 8.4mo); Outcomes and Assessment Methods:; - Height measured by trained staff using wall-mounted measuring board. Weight measured by trained staff using standard floor-model beam scale. Age- and sex-specific BMI calculated based on 2000 CDC growth charts. At risk of overweight (BMI 85th to <95th percentile); Overweight (BMI≥95th percentile); - At baseline, follow-up 6–12mo later (mean 8.4mo) | [underlined: Weight change (lb) per oz/d increase], β (SE), linear regression; Fruit drinks; TEI adj: −0.03 (0.02), P=0.42; Soda; TEI adj: −0.01 (0.04), P=0.81; [underlined: BMI change (kg/m2) per oz/d increase], β (SE), linear regression; Fruit drinks; TEI adj: −0.01 (0.01), P=0.38; Soda; TEI adj: −0.01 (0.02), P=0.50 [Estimates remained similar when TEI was omitted from model. (Data NR). Regression results did not change when beverage variables were modeled as change in intake between visits 1 and 2 (data NR). Similar null results were seen when fruit drinks were dichotomized into ≥12 oz/d (data NR)] | Model Adjustments:; - TEI: yes and no; - Key confounders: Sex, age, race and/or ethnicity, SEP (maternal years of education, poverty level), anthropometry at baseline (weight), diet quality (other beverages); - Other: Birth weight, change in height, residence (town or city, rural, reservation, military base); Limitations:; - Did not account for key confounders: Physical activity; - No preregistered data analysis plan; Funding:; USDA; NIH Health Harvard Education Program in Cancer Prevention Control; Boston Obesity Nutrition Research Center
Nissinen, 2009^73^; PCS, Cardiovascular Risk in Young Finns Study, Finland; Analytic N=2,139; Included in meta-analysis: Yes; Participant characteristics at baseline:; Children; - Age: 10.7y; - Female: 55%; - Race/ethnicity: NR; - SEP: Parental education: ≤9y: ~46%; 10–12y: ~28%; >12y: ~25%; - Anthropometry: Overweight: 7.8%, Obesity: ~1.2%; - Physical activity: ≥30 min in adulthood, <weekly: ~8%, weekly: ~46%, >weekly: ~46%; - Diet quality: NR; - TEI: NR; - Study beverage intake at baseline: Rarely: ~10%; 2–3 times/mo: ~15%; 1 times/wk: ~26%; 2–3 times/wk: ~21%; Nearly every day: ~18%; Daily: ~9%; Excluded from Study or Analysis: participants with incomplete data on weight, height, or consumption of sweets and sugar-sweetened soft drinks | Exposure: Sugar-sweetened soft drinks; Comparator: Continuous intake (units/mo); Categorical intake: Daily/nearly daily, 1–3 times/wk, Less frequently; Categorical change in intake: Increase, Stable high, Stable low, Decrease; Exposure Assessment Methods and Timing:; - Validated questionnaire, how often they consumed sugar-sweetened soft drinks; calculated units/mo (completed by parent/guardian for children 3–6y); - At baseline (1980), 21y (2001); Outcomes and Assessment Methods:; - Weight and height measured by a trained nurse.; BMI calculated as kg/m2; Overweight defined as BMI ≥25 kg/m2; - At baseline (1980), 21y (2001) | [underlined: Adulthood BMI], multivariable linear regression β (SE); Per 10-unit SSB consumption in childhood; Males: 0.01 (0.01), P=0.51; Females: −0.16 (0.14), P=0.24; Per 10-unit change in consumption per month from childhood to adulthood; Males: −0.04 (0.11), P=0.71; Females: 0.45 (0.12), P<0.001; [underlined: Overweight in adulthood], logistic regression, OR (95% CI); Per 10-unit SSB consumption in childhood: NS, Data NR; By change in frequency of consumption from childhood to adulthood; Males; Increase (n=327): 1.07 (0.74, 1.57); Stable high (n=146): 1.13 (0.71, 1.78); Stable low (n=199): Ref; Decrease (n=357): 0.93 (0.62, 1.39); Females; Increase (n=379): 1.90 (1.38, 2.61); Stable high (n=75): 1.71 (0.99, 2.93); Stable low (n=373): Ref; Decrease (n=317): 1.11 (0.79, 1.56); By frequency categories in both childhood and adulthood:; Males: NS, Data NR; Females:; Daily and nearly daily: 2.02 (1.27, 3.23); 1–3 times/wk: 2.00 (1.51, 2.63); Less frequently: 1.00 (95% CI NR) | Model Adjustments:; - TEI: no; - Key confounders: Sex, age, socioeconomic position (parental education), anthropometry at baseline, physical activity; - Other: smoking in adulthood; Limitations:; - Did not account for key confounders: race and/or ethnicity, diet quality; - No preregistered data analysis plan; Dietary assessment at baseline and follow-up only (21y apart); Funding:; Academy of Finland; Finnish Cultural Foundation; Juho Vainio Foundation; Yrjö Jahnsson Foundation
Olsen, 2012^74^; PCS, Danish part of European Youth Heart Study (EYHS), Denmark; Analytic N=359; Included in meta-analysis: No; Participant characteristics at baseline:; 3rd grade children; - Age: ~9.6y; - Female: 56%; - Race/ethnicity: NR; - SEP: NR; - Anthropometry: BMI ~17.2 kg/m^2^; - Physical activity: Physical fitness ~3.0 W/kg; - Diet quality: NR; - TEI: ~2175 kcal/d; - Study beverage intake at baseline: Liquid sucrose intake: ~21 g/d; Excluded from Study or Analysis: Missing exposure and/or outcome data at baseline or follow-up | Exposure: Liquid sucrose (carbonated, SSB with a sucrose content of 10% of volume and sugar-sweetened lemonade); Comparator: Liquid sucrose intake (continuous; per 10g); Exposure Assessment Methods and Timing:; - 24hr dietary recall interview supplemented by a FFQ and a qualitative food record; - At baseline; Outcomes and Assessment Methods:; - Height measured to nearest 5 mm using a stadiometer; Weight measured to nearest 0.1 kg using a beam-scale type weight; Age- and gender-specific BMI z-scores (BMI z-score) generated using LMS method; Waist circumference measured twice (mean was calculated) at the largest circumference of abdomen between ribs and trochanter major; - At baseline (1997–1998), and ~6y follow-up (2003–2004) | [underlined: BMI z-score, Change over 6 years], SD, Linear regression, β (SE); TEI unadj: 0.017 (0.016), P=0.30; TEI adj: 0.006 (0.018), P=0.74; [underlined: WC, Change over 6 years], cm, Linear regression, β (SE); TEI unadj: 0.140 (0.132), P=0.29; TEI adj: 0.151 (0.149), P=0.31 | Model Adjustments:; - TEI: yes and no; - Key confounders: sex, age, socioeconomic position (maternal status/not defined), anthropometry at baseline, physical activity, diet quality (intake of complex carbohydrates, intake of fat); - Other: whether puberty started, school, fasting insulin level, intake of solid sucrose (grams of sucrose from orange juice, apple juice, chocolate milk, milkshake and drinkable yoghurt); Limitations:; - Did not account for key confounders: race and/or ethnicity; - 39% of original sample was excluded due to missing data—no information on how it may have varied across groups; Exposure measured only at baseline; No preregistered data analysis plan; Funding:; Danish Heart Foundation; Danish Medical Research Council; Health Foundation; Danish Council for Sports Research; Foundation of 17–12–1981; Foundation in Memory of Asta Florida Bolding nee Andersen, Faculty of Health Sciences, University of Southern Denmark; Tryg Foundation
Pereyra-Gonzales, 2023^76^; PCS, ENDIS (Encuesta de Nutrición Desarrollo Infantil y Salud), Uruguay Analytic N=542; Included in meta-analysis: Yes; Participant characteristics at baseline:; Children; - Age: 25.1 (10.8)mo; - Female: 48%; - Race/ethnicity: NR; - SEP: Maternal education: 27% University; 24% high school; 49% <high school ; Household income: NR; - Anthropometry: BMIz 0.6 (1.2); - Physical activity: NR; - Diet quality: 75% consumed sugary ultra-processed foods in previous day; - TEI: NR; - Study beverage intake at baseline: 24% consumed SSB in previous day; Excluded from Study or Analysis: children ≥4y; missing dietary data | Exposure: SSB (processed juices and carbonated and non-carbonated drinks with added sugar); Comparator: Categorical intake: No (ref) versus. Yes; Exposure Assessment Methods and Timing:; - Parents complete dietary intake questionnaires. At baseline, the questionnaire assessed children’s food and drink consumption during the previous day (yes/no). At follow-up, the questionnaire assessed children’s food and drink consumption during the previous week (yes/no, plus weekly frequency). Wave 2 data dichotomized by population median frequency of consumption (‘yes’ for consumption above population median and ‘no’ for below the median).; - At baseline (wave 1, 2013–2014), and 2y follow-up (wave 2, 2015–2016); Outcomes and Assessment Methods:; - Weight and length/height were measured by trained staff and used to calculate BMI z-scores based on WHO standards.; - At baseline (wave 1, 2013–2014), and 2y follow-up (wave 2, 2015–2016) | [underlined: Change in BMIz], Linear regression, β (95% CI); By SSB at baseline (versus no SSB at baseline, n=542):; −0.02 (−0.10, 0.06), P=0.59; By SSB at baseline and follow-up (versus no SSB at baseline and follow-up, n=209): −0.03 (−0.05, 0.12), P=0.41 | Model Adjustments:; - TEI: no; - Key confounders: sex, age, socioeconomic position (household income), anthropometry at baseline; - Other: child birthweight, breastfeeding duration, spacing between measurements in months, province of residence in wave 2; Limitations:; - Did not account for key confounders: race and/or ethnicity, physical activity, diet quality; - Exposure subject to measurement error; High attrition/missing data with no information on non-completers; No preregistered data analysis plan; Funding:; ANII/Doctorado en el exterior; Universidad de Chile/Ayudas para Estadías Cortas de Investigación
Phillips, 2004^77^; PCS, Massachusetts Institute of Technology Growth and Development Study, U.S.; Analytic N=178; Included in meta-analysis: Yes; Participant characteristics at baseline:; Children, girls; - Age: 10.0 (0.93)y; - Female: 100%; - Race/ethnicity: White: 75%; Black: 14%;; Other: 11%; - SEP: NR; - Anthropometry: BMI, Mean (SD): 16.6 (1.8) kg/m2; BMI z-score: −0.27 (0.89); - Physical activity: Activity time, Mean (SD): 4.1 (1.6) hr/d; - Diet quality: Energy-dense snack foods (baked goods, ice cream, chips, soda, candy), Mean (SD): 2.3 (1.7) svg/d, 15.7 (8.1) % daily kcal; - TEI: Mean (SD), 2021 (669) kcal/d; - Study beverage intake at baseline: % daily kcal from soda: Mean (SD), 2.7 (3.9); Excluded from Study or Analysis: annual visits when participants left >12 items blank on FFQ or when daily energy intake <500 or >5000 kcal as calculated from FFQ; participants with fewer than 3 annual visits were excluded | Exposure: Sugar-sweetened soda; Comparator: Categorical intake (quartiles, % of kcal); Exposure Assessment Methods and Timing:; - Validated semiquantitative FFQ representing intake in the past year; - Annually for 10y; Outcomes and Assessment Methods:; - Height measured with wall-mounted stadiometer; Weight measured with Seca scale; BMI z-score calculated using CDC 2000 growth charts; %BF estimated using prediction equations; - Annually for 10y | [underlined: BMI z-score, by % kcal from soda], linear mixed effects regression, β; First quartile (<0.74): Ref; Second quartile (0.75-1.4): 0.089, P=0.030; Third quartile (1.5-3.1): 0.172, P<0.001; Fourth quartile (≥3.2): 0.178, P=0.001; P for trend: <0.001; [underlined: %Body Fat, by % kcal from soda], linear mixed effects regression, β; First quartile (<0.74): REF; Second quartile (0.75-1.4): 0.15, P=0.57; Third quartile (1.5-3.1): 0.41, P=0.18; Fourth quartile (≥3.2): 0.31, P=0.35; P for trend: <0.001 | Model Adjustments:; - TEI: no; - Key confounders: Sex, age, race and/or ethnicity, physical activity, diet quality (fruits, vegetables, energy-dense snacks); - Other: Age at menarche; inactivity time; parental overweight; % daily kcal from carbohydrates, protein, and fat; Limitations:; - Did not account for key confounders: socioeconomic position, anthropometry at baseline; - No information on non-completers; No preregistered data analysis plan; Funding:; NIH; Mars, Inc.
Quah, 2019^78^; PCS, Growing Up in Singapore Towards healthy Outcomes (GUSTO), Singapore; Analytic N=767 (5y data); Included in meta-analysis: Yes; Participant characteristics at baseline:; Children of Asian Singaporean mothers; - Age: 5y; - Female: 49%; - Race/ethnicity: Mothers: Chinese: 60%; Malay: 28%; Indian: 12%; - SEP: 63% post-secondary and below; 37% university and above; University and above: T1 42.5%, T2 32.3%, T3 31.6%; - Anthropometry: BMI z-score at 5y, mean (SD): T1: −0.19 (1.0); T2: 0.08 (1.3), T3 0.20 (1.3); SSF at 5y, mm, mean (SD): T1: 27.5 (8.8); T2: 28.9 (10.3); T3: 29.9 (11.1); - Physical activity: Outdoor play at 3y: ~87% <2h/d; ~12% 2-4 h/d; ~0.6% >4h/d; - Diet quality: NR; - TEI: At 5y, kcal/d, mean (SD): T1: 1245 (431); T2: 1405 (435); T3: 1735 (627); - Study beverage intake at 5y: mL/d Median (IQR); T1: 40 (21, 57) mL/d; T2: 111 (93, 137) mL/d; T3: 241 (197, 328) mL/d; 98% reported child consuming some form of SSB; Excluded from Study or Analysis (pregnancy cohort): nonhomogeneous ethnic background (up to the four grandparents of the offspring), intention not to deliver in the study centres or not to remain in Singapore for the following 5 years. Excluded from current analysis: missing exposure or outcome data. | Exposure: SSBs (carbonated, non-carbonated, fruit juices containing added sugar, malted drinks, cultured milk drinks, soya-based drinks, barley water, chrysanthemum tea, herbal tea). Daily intake (mL/d) quantified by multiplying frequency of consumption per d by volume of intake for each beverage.; Comparator: Continuous intake (100 mL/d) and categorical intake (tertiles, mL/d); Exposure Assessment Methods and Timing:; - Validated FFQ administered by trained interviewers; - At 5y; Outcomes and Assessment Methods:; - Weight, height and four skinfold thicknesses (triceps, biceps, subscapular and supra-iliac) measured by trained staff in duplicate; Sum of skinfolds (SSF) summed from averages of each type. BMI z-score calculated based on 2007 WHO references; Overweight or obesity ≥1 SD above reference distribution.; - At 6y | [underlined: BMI z-score at 6y by intake at 5y] (n=767); SSB intake per 100 mL/d, Linear regression, β (95% CI); Energy unadj: 0.09 (0.03, 0.15), p<0.05; Energy adj: 0.09 (0.02, 0.16), p<0.05; Categorical by tertiles, median (IQR), mL/d; Energy unadj; T1: Ref; T2: 0.17 (−0.05, 0.38); T3: 0.33 (0.11, 0.55), p<0.05; p-trend=0.003; Energy adj; T1: Ref; T2: 0.17 (−0.05, 0.39); T3: 0.34 (0.11, 0.58), p<0.05; p-trend=0.004; [underlined: Sum of skinfold thickness by intake at 5y] (n=619); SSB intake per 100 mL/d, Linear regression, β (95% CI); Energy unadj: 0.75 (0.06, 1.44), p<0.05; Energy adj: 0.87 (0.14, 1.60), p<0.05; Categorical by tertiles, median (IQR), mL/d; Energy unadj; T1: Ref; T2: 0.53 (−1.89, 2.94); T3: 1.93 (−0.52, 4.37); p-trend=0.123; Energy adj; T1: Ref; T2: 0.62 (−1.81, 3.04); T3: 2.20 (−0.38, 4.78); p-trend=0.096; [underlined: Risk of OW/OB at 6y by intake at 5y] (n=767); SSB intake per 100 mL/d, Multivariate Poisson regression, RR (95% CI); Energy unadj: 1.15 (1.07, 1.23), p<0.01; Energy adj: 1.15 (1.06, 1.24), p<0.05; Categorical by tertiles, median (IQR), mL/d; Energy unadj; T1: Ref; T2: 1.13 (0.74, 1.71); T3: 1.56 (1.05, 2.33), p<0.05; p-trend=0.025; Energy adj; T1: Ref; T2: 1.12 (0.74, 1.69); T3: 1.54 (1.03, 2.30), p<0.05; p-trend=0.033 | Model Adjustments:; - TEI: yes and no; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position (mother’s education); - Other: birth weight for gestational age; screen time; BF duration; parity; maternal BMI 48mo postpartum (5y exposure analysis only), SSB intake at 18mo (5y exposure analysis only); Limitations:; - Did not account for key confounders: anthropometry at baseline, physical activity, diet quality; - High attrition/missing data; No preregistered data analysis plan; Funding:; Singapore National Research Foundation; Singapore Institute for Clinical Sciences, National Institute for Health Research, European Union’s Erasmus+ Capacity-Building ENeA Project and Seventh Framework Program
Quick, 2013^79^; PCS, Project EAT (Eating and Activity in Teens and Young Adults), U.S.; Analytic N=1,643; Included in meta-analysis: Yes; Participant characteristics at baseline: adolescents without overweight; - Age: 15 (1.6)y; - Female: 54%; - Race/ethnicity: White: 49%; Black: 18%; Asian: 18%; Native American: 3%; Multi-racial/other: 5%; Hispanic: 6%; - SEP: Low: 16%; Low-middle: 18%; Middle: 25%, Middle-high: 23%; High: 13%; - Anthropometry: Incidence of overweight in original sample (n=2134): 24.8%; No participants with overweight at baseline in sample analyzed for GBCO outcomes.; - Physical activity: Moderate and vigorous physical activity, hr/wk, mean (SD); Females: 5.9 (4.4); Males: 7.6 (4.6); - Diet quality: svg/d, Mean (SD); Fruit intake: Females: 2.2 (1.7); Males: 2.2 (1.6); Vegetable intake: Females: 1.8 (1.3); Males: 1.6 (1.4); Whole grain intake: Females: 0.9 (0.8); Males: 1.1 (0.9); Fast food intake, times/wk, Mean (SD) Females: 1.6 (1.6); Males: 1.8 (1.6); - TEI: Mean (SD):; Females: 1941 (835) kcal/d; Males: 2271 (1127) kcal/d; - Study beverage intake at baseline: Mean (SD): Females: 1.0 (0.9) svg/d; Males: 1.3 (0.9) svg/d; Excluded from Study or Analysis: with overweight at baseline, lost to follow up; missing data; pregnancy at follow-up | Exposure: Soda, not otherwise defined; Comparator: Continuous intake (svg/d), baseline-only and 10y change in intake; Exposure Assessment Methods and Timing:; - 2007 Willett semi-quantitative FFQ (at Time 3); youth form of questionnaire administered at Time 1; - Baseline, 10y; Outcomes and Assessment Methods:; - self-reported ht and wt used to calculate BMI; overweight status at baseline determined based on BMI ≥85th percentile for sex and age (CDC data); overweight status at 10y follow-up defined as ≥25 kg/m2; - Baseline, 10y | [underlined: Incidence of Overweight by baseline SSB intake], OR (95% CI), logistic regression; Females: 1.14 (0.95, 1.38); Males: 1.09 (0.91, 1.31); [underlined: Incidence of Overweight by 10y change in SSB intake], OR (95% CI), logistic regression; Females: 1.09 (0.93, 1.27); Males: 1.06 (0.94, 1.21) | Model Adjustments:; - TEI: yes; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position; - Other: Time point 1 intake of SSB; Limitations:; - Did not account for key confounders: physical activity, diet quality, anthropometry at baseline; - Exposure not well defined; High attrition with no information on non-completers; height and weight were self-reported; No preregistered data analysis plan; Funding:; NHLBI
Seo, 2015^80^; PCS, Healthy, Energetic, Ready, Outstanding, Enthusiastic Schools (HEROES) Initiative (NRCT), U.S.; Analytic N=5,309; Included in meta-analysis: Yes; Participant characteristics at baseline: 4th-12th grade children participating in a school-based intervention; - Age: 10.8 (3.2) y; - Female: 50%; - Race/ethnicity: White 81%; Nonwhite 19%; - SEP: School lunch: 51% Eligible for free or reduced-price lunch; - Anthropometry: BMI percentile, 68.4 (28.0); - Physical activity: NR; - Diet quality: NR; - TEI: NR; - Study beverage intake at baseline: NR; Excluded from Study or Analysis: missing data | Exposure: Soda intake, not diet; Comparator: Soda intake (continuous; times/d); Exposure Assessment Methods and Timing:; - Student Health Assessment Questionnaire (adapted from Schools Physical Activity and Nutrition Survey Questionnaire and pilot tested); “Yesterday, how many times did you drink a full serving of regular (not diet) soda?”; - At baseline, 6, 12, and 18mo follow-up; Outcomes and Assessment Methods:; - Height measured by two trained staff using a stadiometer; Weight measured by two trained staff using a digital scale; BMI calculated as kg/m2. Age- and sex-adjusted BMI percentiles and weight status categories based on 2009 CDC growth charts: Underweight (<5th%), Normal (5th-84.9th%), with overweight (85th-94.9th%), with obesity (≥95th%) Weight status: Persistent without overweight or without obesity (stayed normal or underweight during 18mo study period); Persistent with overweight or obesity (stayed with overweight or obesity during 18mo study period); Deteriorated weight (moved from normal/underweight to with overweight/obesity then stayed with overweight/obesity, or from with overweight to with obesity and then remained with obesity); Improved weight (those who lost weight and moved to and maintained normal/underweight status); - At baseline, 6, 12, and 18mo follow-up | [underlined: Weight Status, change during 18mo study period per continuous soda intake], Logistic regression, OR (95% CI); Persistent non-overweight (n=2929, ref) versus.; Persistent overweight/obesity (n=1627): 1.07 (1.03, 1.11), P=0.0016; [underlined: Deteriorated weight (normal/underweight to overweight/obesityesity, or overweight to obesity]; n=364); 1.08 (1.01, 1.15), P=0.0278; [underlined: Improved weight (overweight/obesity to normal, obesity to overweight]; n=330); 0.93 (0.85, 1.02), P=0.1356 | Model Adjustments:; - TEI: no; - Key confounders: age, anthropometry at baseline; - Other: School (cluster); Limitations:; - Did not account for key confounders: sex, race and/or ethnicity, socioeconomic position physical activity, diet quality; - No information on baseline N or attrition, Exposure (soda intake) measured using single question representing previous day only and not well-defined, No preregistered data analysis plan; Funding:; Wellborn Baptist Foundation; National Research Foundation of Korea
Seum, 2022^81^; PCS, BELLA study, a module of the German National Health Interview and Examination Survey (KiGGS), Germany; Analytic N=460; Included in meta-analysis: No; Participant characteristics at baseline:; children and adolescents 11-17y; - Age: 14.0y; - Female: 53%; - Race/ethnicity: 6.5% migration status (immigrated from another country and ≥1 parent not born in Germany, or both parents immigrated and/or had non-German citizenship); - SEP: Parent education: 13.77 (2.3)y; - Anthropometry: BMI 22.6 (3.98) kg/m2; - Physical activity: 3.93 (1.78) days/wk; - Diet quality: NR; - TEI: NR; - Study beverage intake at baseline: 7.24 (14.74) SSB glasses/wk; Excluded from Study or Analysis: Missing data | Exposure: Sugar-sweetened beverages, not otherwise defined. 1 glass = 200 mL; Comparator: Continuous intake, glasses SSB/wk; Exposure Assessment Methods and Timing:; - 2 questions on frequency of SSB consumption (every day, at least once/wk, less than once/wk, never) and amount of SSB consumption (glasses of SSB per day or per week).; - Baseline (2009-2012); Outcomes and Assessment Methods:; - Height and weight were measured by study personnel and used to calculate BMI.; - At ~5y follow-up (2014-2017) | [underlined: BMI (kg/m2) at 5y follow-up by baseline SSB intake], β (95% CI), mediation analysis; 0.01 (−0.1, 0.04), p=0.259 | Model Adjustments:; - TEI: no; - Key confounders: sex, age, socioeconomic position; - Other: migration status; Limitations:; - Did not account for key confounders: race and/or ethnicity, anthropometry at baseline, physical activity, diet quality; - Exposure was not well defined and was subject to measurement error; Outcomes were only measured at f/u; No preregistered data analysis plan;; Funding:; German Federal Ministry of Health
Shroff, 2014^82^; PCS, Bogotá School Children Cohort, Colombia; Analytic N=890; Included in meta-analysis: Yes; Participant characteristics at baseline:; Children; - Age: 8.6 (1.7)y; - Female: 51%; - Race/ethnicity: Born in Bogotá ~86%; - SEP: Mother’s education ~8.6y; Low ~43%;; - Anthropometry: BMI z-score, Mean (SD): 0.12 (1.02); BMI z-score>1: 18%; BMI z-score>2: 4%; - Physical activity: Time playing outside ~17.3 hr/wk; - Diet quality: NR; - TEI: ~6440 kJ/d; - Study beverage intake at baseline: Never to <1/mo: 31%; 1/wk to 1/mo: 38%; 2-6/wk: 20%; ≥1/d: 10%; Excluded from Study or Analysis: not randomly selected in sample of children 5-12y from public primary schools and low- and middle-income families in Bogotá, Colombia; missing exposure data | Exposure: Soda intake; Comparator: Categorical intake: Never (ref), <1/mo, 1/wk to 1/mo, 2-6/wk, ≥1/d; Exposure Assessment Methods and Timing:; - FFQ (completed by mother) administered by trained dietitians 4-d dietary record completed by parents; represents usual dietary intake during the previous month; - Baseline; Outcomes and Assessment Methods:; - Height, weight, WC, and triceps and subscapular SF measured by trained research staff using standard protocol; - Baseline (2006), 2007, and 2008 | [underlined: Sum of skinfold thickness], mm, annual change, linear regression, Mean (95% CI); Never (n=110, ref) versus; <1/mo (n=184): 0.009 (−0.005, 0.023); 1/wk to 1/mo (n=356): 0.001 (−0.011, 0.013); 2-6/wk (n=187): 0.007 (−0.006, 0.020); ≥1/d (n=98): 0.014 (−0.002, 0.030); P trend: 0.24; [underlined: Waist circumference], cm, annual change, linear regression, Mean (95% CI); Never (n=110, ref) versus; <1/mo (n=184): −0.1 (−0.8, 0.5); 1/wk to 1/mo (n=356): 0.3 (−0.3, 0.9); 2-6/wk (n=187): 0.3 (−0.4, 0.9); ≥1/d (n=98): 0.6 (−0.1, 1.4); P trend: 0.04; [underlined: BMI, annual change], kg/m2, linear regression, Mean (95% CI); Never (n=110, ref) versus; <1/mo (n=184): 0.06 (−0.06, 0.19); 1/wk to 1/mo (n=356): 0.11 (0.00, 0.22); 2-6/wk (n=187): 0.12 (−0.01, 0.25); ≥1/d (n=98): 0.20 (0.04, 0.36); P trend: 0.01 | Model Adjustments:; - TEI: yes; - Key confounders: Sex, age, SEP (low SES), anthropometry at baseline; - Other:; Limitations:; - Did not account for key confounders: race and/or ethnicity, physical activity, diet quality; - No information on how missing data were handled; Exposure not well defined; Exposure only measured at baseline; No preregistered data analysis plan; Funding:; ASISA Research Fund at the University of Michigan
Sichieri, 2013^83^; PCS, Rio de Janeiro Study, Brazil; Analytic N=1,134; Included in meta-analysis: Yes; Participant characteristics at baseline:; Children, 4th graders participating in a RCT; - Age: NR; - Female: 53%; - Race/ethnicity: NR; - SEP: NR; - Anthropometry: BMI: ~18.2 kg/m2; - Physical activity: NR; - Diet quality: NR; - TEI: NR; - Study beverage intake at baseline: ~0.6 glasses/d, ~250 mL/d; Excluded from Study or Analysis: participants in any grade other than 4^th^ grade; not participating in a RCT in a metropolitan area of Rio de Janeiro | Exposure: Soda intake (colas and other sodas); Comparator: Continuous intake (glass/d); Exposure Assessment Methods and Timing:; - Single 24h recall, supplemented by a drinking frequency questionnaire representing usual intake; - Baseline; Outcomes and Assessment Methods:; - Height, weight measured using standard methods; BMI calculated as kg/m2; BMI z-score categories based on WHO; - At baseline (beginning of school year) and end of same school year | [underlined: BMI], kg/m2, linear regression, β (95% CI) Change per glass/d increase: 0.11 (0.03, 0.25), P=0.002 | Model Adjustments:; - TEI: no; - Key confounders: sex, age; - Other:; Limitations:; - Did not account for key confounders: Race and/or ethnicity, SEP, physical activity, diet quality; - No information on baseline N or attrition; Exposure measured at baseline only; Exposure poorly defined; No preregistered data analysis plan; Funding:; Brazilian National Research Institute
Stoof, 2013^85^; PCS, Amsterdam Growth and Health Longitudinal Study (AGAHLS), Netherlands; Analytic N=238; Included in meta-analysis: Yes; Participant characteristics at baseline:; adolescents; - Age: 13 (0.6)y; - Female: 52%; - Race/ethnicity: NR; - SEP: “all participants came from the same neighborhood and had a similar SES (moderate to high)”; - Anthropometry: mean BMI~24.4 kg/m2; - Physical activity: ~625 MET x min/d; - Diet quality: NR; - TEI: ~10346 kJ/d (2494 kcal/d); - Study beverage intake at baseline: Sugar-containing beverages, mL/d, Mean (SD); Female: 160 (137); Male: 200 (191); Excluded from Study or Analysis: missing exposure, outcome or covariate data | Exposure: carbonated and uncarbonated sugar-sweetened drinks such as soda, lemonade, iced tea, sports drinks and energy drinks, fruit drinks (diluted and sugar-sweetened fruit juices)). Did not include diet (low-energy) soft drinks, other non-caloric beverages, alcoholic beverages, milk and other liquid dairy products. (220 ml = 1 svg); Comparator: SCB intake (continuous; svg/d); Exposure Assessment Methods and Timing:; - Cross-check dietary history face-to-face interviews by a dietitian (parents also questioned on details of food items); represents usual intake during previous month; - At baseline (1976); Outcomes and Assessment Methods:; - Weight and height measured by trained nurse according to standard procedures with participants wearing only underwear; - BMI calculated as kg/m2; - Total body fat mass, %total fat, and %trunk fat measured using DXA; - Overweight (BMI≥25 kg/m2) and obesity (BMI≥30 kg/m2) in adulthood defined according to WHO standards; - At baseline, and 24 and/or 30y follow-up (2000 and/or 2006); if values were available for 2000 and 2006, the avg was used | [underlined: Associations between SSB intake (svg/d) at 13yo and body composition 25-30y later;] β (95% CI); MALES (n=114); % Total Fat:; TEI unadj: 1.10 (−0.02, 2.21), P=0.05; TEI adj: 1.14 (0.04, 2.23), P=0.04; % Trunk Fat:; TEI unadj: 1.57 (0.07, 3.08), P=0.04; TEI adj: 1.62 (0.14, 3.10), P=0.03; FEMALES (n=124); % Total Fat:; TEI unadj: −0.72 (−2.40, 0.97), P=0.40; TEI adj: −0.72 (−2.44, 1.01), P=0.41; % Trunk Fat:; TEI unadj: −0.77 (−2.88, 1.35), P=0.48; TEI adj: −0.85 (−3.02, 1.31), P=0.44; [underlined: Associations between SSB intake (svg/d) at 13yo and BMI 25-30y later]; β (95% CI); MALES (n=114); BMI:; TEI unadj: 0.24 (−0.34, 0.81), P=0.42; TEI adj: 0.24 (−0.33, 0.82), P=0.41; FEMALES (n=124); BMI:; TEI unadj: 0.44 (−0.37, 1.24), P=0.28; TEI adj: 0.43 (−0.39, 1.25), P=0.30 | Model Adjustments:; - TEI: yes and no; - Key confounders: sex, age, anthropometry at baseline, socioeconomic position, physical activity; - Other:; Limitations:; - Did not account for key confounders: race and/or ethnicity, diet quality; - Attrition 42% without information on non-completers, Exposure measured only at baseline, Validation of exposure data collection tool not indicated, No preregistered data analysis plan; Funding:; Dutch Heart Foundation; Dutch Prevention Fund; Dutch Ministry of Well Being and Public Health; Dairy Foundation on Nutrition and Health; Dairy Foundation on Nutrition and Health; Dutch Olympic Committee/Netherlands Sports Federation; Heineken Inc.
Striegel-Moore, 2006^86^; PCS, NHLBI Growth and Health Study, U.S.; Analytic N=2,371; Included in meta-analysis: Yes; Participant characteristics at baseline:; Female adolescents; - Age: ~10y; - Female: 100%; - Race/ethnicity: White 49%; Black 51%; - SEP: <$10K: 17%; $10<20K: 14%; $20<30K: 15%; $30<40K: 14%; $40<50K: 12%; $50<75K: 17%; ≥$75K: 6%; - Anthropometry: Weight: ~ 37kg; Height: ~141 cm; - Physical activity: NR; - Diet quality: NR; - TEI: NR; - Study beverage intake at baseline: Mean (SE), g/d; Soda intake: White, 135.5 (8.3); Black, 134.5 (7.9); Fruit drink intake: White, 78.4 (4.4); Black, 134.7 (6.8); Excluded from Study or Analysis: Male sex; age <9y or >10y at baseline; those who did not identify as “Black” or “white”, non-Hispanic; racially discordant parents or guardians | Exposure: Soda (non-diet, carbonated), fruit drinks (Sweetened non-carbonated fruit-flavored drinks, punches, or ades, bottled, canned, frozen; excludes artificially sweetened non-carbonated drinks, sports drinks); Comparator: Continuous intake, 100g/d; Exposure Assessment Methods and Timing:; - Validated 3-d food records; represents usual intake over 3 consecutive days (2 weekdays and 1 weekend day); - At baseline, and annually for years 1-5, then at years 7, 8, 10; Outcomes and Assessment Methods:; - Weight measured twice by research staff using electronic scale. Height measured twice by research staff using stadiometer. BMI calculated as weight in kilograms divided by height in meters squared; - Baseline, annually until 10y follow-up | [underlined: BMI, change per 100g/d increase], β (SE), linear regression; Regular soda: 0.011 (0.005), P<0.05; Fruit drinks: 0.009 (0.007), P>0.05 | Model Adjustments:; - TEI: yes; - Key confounders: Sex, age, race and/or ethnicity; - Other: Study site; Limitations:; - Did not account for key confounders: SEP, anthropometry at baseline, physical activity, diet quality; - No information on non-completers; No preregistered data analysis plan; Funding:; NHLBI
Tam, 2006^87^; PCS, Nepean Study, Australia; Analytic N=281; Included in meta-analysis: No; Participant characteristics at baseline:; Australian children; - Age: 7.7 (0.6)y; - Female: 5000%; - Race/ethnicity: NR; - SEP: NR; - Anthropometry: Normal BMI at 7y & 13y: 69%; BMI gainers: Normal BMI at 7y & with overweight/obesity at 13y: 11%; BMI losers: with overweight/obesity at 7y & with normal BMI at 13y: 5% with overweight/obesity at both 7y & 13y: 15%; - Physical activity: NR; - Diet quality: NR; - TEI: NR; - Study beverage intake at baseline: NR; Excluded from Study or Analysis: born preterm, incomplete data at baseline or follow up | Exposure: Soft drink/cordial (sugar sweetened); fruit juice/drink (unclear if 100% juice); Comparator: Continuous intake, level of SSB (soft drink/cordial) or juice/drink; Exposure Assessment Methods and Timing:; - Estimated (household measurement) 3-day food record; - 7.7y; Outcomes and Assessment Methods:; - Height and weight measured by study staff; CDC growth charts (2005) were used to determine overweight/obesity; - Follow-up time: Mean (Range) 5.4 (4.0-6.6)y; Follow-up age: Mean (SD); 13.0 (0.2)y | [underlined: Weight status], Median g of carbohydrate intake from beverage per day (5th-95th percentile), Kruskal-Wallis test; SSB (soft drink/cordial);; Acceptable BMI (n=195): 20 (0-71)g; BMI gainers (n=32): 29 (0-92)g; BMI losers (n=13): 6.5 (0-170)g; With overweight/obesity at both time points; (n=41): 30 (0-108)g; P=0.005; Fruit juice/drink; Acceptable BMI (n=195): 14 (0-48); BMI gainers (n=32): 8.6 (0-59); BMI losers (n=13): 13 (0-41.4); With overweight/obesity at both time points; (n=41): 14 (0-44); P=0.734 | Model Adjustments:; - TEI: No; - Key confounders: Sex, age, anthropometry at baseline; - Other:; Limitations:; - Did not account for key confounders: Race/ethnicity, socioeconomic position, physical activity, diet quality; - Exposure not well defined; Exposure data only measured at baseline; No information on non-completers; No preregistered data analysis plan; Funding:; NR; broader cohort funding provided by the Children’s Hospital Clinical Research Grant Program and Pharmacia & Upjohn (Garnett, 2001)
Thurber, 2017^88^; PCS, Longitudinal Study of Indigenous Children (LSIC), Australia; Analytic N=895; Included in meta-analysis: Yes; Participant characteristics at baseline:; Indigenous Australian children with normal BMI; - Age: 62% ≤5y (3-6y); 34% >5y; - Female: 50%; - Race/ethnicity: 88% Aboriginal; 7% Torres Strait Islander; 5% Both; - SEP: 59% < 12y education; ; 13% Run out of money, 50% Just enough money, 36% Can save money; 8.3% Went without meals in past year; Area-level disadvantage: 19% most advantaged, 61% middle advantage, 20% most disadvantaged; Primary caregiver: 70% Not employed; - Anthropometry: ~9% Overweight, 3% Obesity at Wave 3; - Physical activity: NR; - Diet quality: NR; - TEI: NR; - Study beverage intake at baseline: 31% with ≥2 occasions on preceding day; Excluded from Study or Analysis: Not Indigenous; not aged 0.5-2y and 3.5-5y in 2008 (Wave 1); No BMI recorded at Wave 3; BMI outside “normal” range based on established BMI z-score cutoff points from WHO | Exposure: SSB intake (soft drink, cordial, or sports drink – not diet); Comparator: Categorical intake: <2 occasions on preceding day versus. ≥2 occasions on preceding day; Exposure Assessment Methods and Timing:; - Parent-report 24-hr recall; represents consumption from previous day; - Baseline (Wave 3); Outcomes and Assessment Methods:; - Height and weight measured using valid methods. BMI calculated as kg/m2; - Baseline (Wave 3), and annually for 3y (Waves 4-6) | [underlined: BMI intercept at 3y follow-up], difference from referent (95% CI), multilevel growth model, n=887; ≥2 occasions on preceding day: REF; < 2 occasions on preceding day: −0.20 (−0.39, −0.01), p<0.05; [underlined: Annual BMI change by baseline SSB intake], difference in slope coefficient from referent (95% CI), multilevel growth model, n=887; ≥2 occasions on preceding day: REF; < 2 occasions on preceding day: −0.05 (−0.14, 0.03); p=NS; [underlined: BMI change over 3y, per occasion of SSB intake on preceding day], Chi-square analysis, Mean (95% CI) , n=895; ≥2 (n=173): 1.2 (0.9. 1.5); <2 (n=409): 0.9 (0.7, 1.1); [underlined: BMI change over 3y, per occasion of SSB intake on preceding day], Chi-square analysis; %, n=895; Decrease (mean annual BMI z-score ∆ ≤0.3); ≥2: 6.9%; <2: 13.7%; P=NS (NR); No change (mean annual BMI z-score ∆ −0.3-0.3); ≥2: 60.7%; <2: 58.9%; P=NS (NR); Increase (mean annual BMI z-score ∆ ≥0.3); ≥2: 32.4%; <2: 27.4%; P=NS (NR) | Model Adjustments:; - TEI: no; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position (disadvantage) - only in BMI intercept and annual BMI change (slope) analyses); anthropometry at baseline; - Other: Screen time, high-fat food consumption, remoteness (only in BMI intercept and annual BMI change (slope) analyses); Limitations:; - Did not account for key confounders: physical activity, diet quality; - Exposure assessment tool not validated; Exposure data only measured at baseline; No information on portion size; High attrition/missing data with no information on non-completers; No preregistered data analysis plan; Funding:; Australian National University; National Health and Medical Research Council of Australia
Traub, 2018^89^; PCS, Baden-Württemberg Study , Germany; Analytic N=1,733; Included in meta-analysis: Yes; Participant characteristics at baseline:; children participating in school intervention\; - Age: 7.08 (0.63)y; - Female: 49%; - Race/ethnicity: 31% history of migration; - SEP: 32.4% tertiary family education level, 12.6%; ; 12.6% household income ≤ 1750 €; 10% single parent; - Anthropometry: 10% with Overweight, 4% with Obesity, 8% Abdominal with Obesity; - Physical activity: 27% Physically active ≥4 d/wk ≥60 min/d; 69% Play outside; > 60 min/d; - Diet quality: NR; - TEI: NR; - Study beverage intake at baseline: Soft drink intake: 25% >1 time/wk; At school: 7%; Outside school: 24%; Excluded from Study or Analysis: missing data | Exposure: Soft drink intake; Comparator: Categorical intake: Soft drink intake ≤1/week (Ref) versus.; >1/week; Exposure Assessment Methods and Timing:; - Questions on soft drinks at school and outside school assess on a 6-point Likert scale; represents frequency of intake during the week; - At baseline, 1y follow-up; Outcomes and Assessment Methods:; - Height measured by trained staff to the nearest 0.1 cm using stadiometer; Weight measured by trained staff to the nearest 0.1 kg using electric calibrated and balanced scale. Waist circumference measured by trained staff to the nearest 0.1 cm using a flexible metal tape. Age- and gender specific BMI percentile cut-offs based on German reference data: with overweight (>90th%) and with obesity (>97th%). Waist-to-height ratio calculated; Abdominal obesity: defined as waist-to-height ratio ≥0.5; - At baseline, 1y follow-up | [underlined: Changes in BMI%,] Linear mixed effects regression, β (SE); Soft drink >1/wk: −0.75 (0.70), P=0.282; [underlined: Abdominal Obesity at 1y follow up],; Generalized linear mixed effects regression, OR (95% CI); Soft drink >1/wk: 1.46 (0.92, 2.32), P=0.108; [underlined: Changes in Waist-to-Height Ratio], Linear mixed effects regression, β (SE); Soft drink >1/wk: −0.01 (0.15), P=0.966; [underlined: Overweight at 1y follow up], Generalized linear mixed effects regression, OR (95% CI); Soft drink >1/wk: 1.29 (0.84, 1.96), P=0.246; [underlined: Obesity at 1y follow up], Generalized linear mixed effects regression, OR (95% CI); Soft drink >1/wk: 1.57 (0.82, 3.03), P=0.177; [underlined: Changes in Weight], Linear mixed effects regression, β (SE); Soft drink >1/wk: −0.08 (0.09), P=0.385 | Model Adjustments:; - TEI: no; - Key confounders: sex, age, socioeconomic position (family education and household income), anthropometry at baseline; - Other: School, migration status, assignment to intervention or control group; Limitations:; - Did not account for key confounders: race and/or ethnicity, physical activity, diet quality; - No information on baseline N or attrition, Exposure not well defined, Exposure data collection tool not validated, No preregistered data analysis plan; Funding:; Baden-Württemberg Stiftung
Trier, 2016^90^; PCS, Denmark; Analytic N=1,349; Included in meta-analysis: Yes; Participant characteristics at baseline:; Children enrolled in an obesity treatment program; - Age: 11.5y; - Female: 55%; - Race/ethnicity: NR; - SEP: NR; - Anthropometry: BMI SDS: median 2.96 (Range: 1.65–6.12); - Physical activity: NR; - Diet quality: Fast food intake: median 1.5 svg/mo; Range: 0.0-30.0 svg/mo; - TEI: NR; - Study beverage intake at baseline: Median: 1.3 L/wk (Range: 0.0–17.5 L/wk); Excluded from Study or Analysis: Age <3y or >8y; BMI <1.64 equivalent to the 95^th^ percentile per Danish reference charts; <2 clinic visits; no data on consumption at baseline | Exposure: SSB, including soft drinks, juice, lemonade, ice tea and cocoa; approximated in L/wk; Comparator: Categorical intake: Low intake: ≤0.75 L/wk; Medium intake: 0.76 to 2.24 L/wk; High intake: ≥2.25 L/wk; Exposure Assessment Methods and Timing:; - Structured diet interviews by pediatrician; - Baseline; Outcomes and Assessment Methods:; - Weight and height measured by study staff using valid methods; BMI calculated from height and weight. BMI standard deviation score (SDS) calculated by the least mean squares method based on a Danish reference; - Baseline, at each subsequent visit (~every 6wk); median follow-up: 1.3y; maximum follow-up: 5.9y | [underlined: Differences in BMI SDS changes over median 1.3y]: estimate (95% CI), general linear mixed model; SSB High intake versus Medium intake; Boys: 0.009 (−0.056,0.074), p=0.79; Girls: 0.012 (−0.033,0.057), p=0.61; SSB Low intake versus Medium intake; Boys: 0.027 (−0.39,0.093), p=0.42; Girls: 0.034 (−0.008,0.075), p=0.11 | Model Adjustments:; - TEI: no; - Key confounders: sex, age; - Other:; Limitations:; - Did not account for key confounders: race and/or ethnicity, socioeconomic position, anthropometry at baseline, physical activity, diet quality; - Unclear if exposure assessment tool is validated; Exposure data only measured at baseline; No preregistered data analysis plan; Funding:; The Danish Innovation Foundation, The Region Zealand Health Scientific Research Foundation; the Novo Nordisk Foundation
Vanselow, 2009^92^; PCS, Project EAT, U.S.; Analytic N=2,294; Included in meta-analysis: Yes; Participant characteristics at baseline:; Adolescents; - Age: 14.9y; - Female: 55%; - Race/ethnicity: 62.9% white; 9.7% African American; 17.9% Asian American; 2.7% American Indian, 2.9% mixed/other; 3.9% Hispanic; - SEP: ~16% “highest” parent education level (highest), unclear what “highest” means; Soft drinks: 0 svg/wk: 18.8%, 0.5-6 svg/wk: 18.8%, ≥7 svg/wk: 14.2%, P<0.05; - Anthropometry: NR; - Physical activity: ~4 hr/wk strenuous exercise, hr/wk, mean (SE), chi-square test; Soft drinks: 0 svg/wk: 4.1 (0.1), 0.5-6 svg/wk: 3.9 (0.0), ≥7 svg/wk: 3.9 (0.1), P>0.05; - Diet quality: Saturated fat, fiber, and calcium intake by beverage type available in paper; - TEI: ~2000 kcal/d, mean (SE), chi-square test; Soft drinks: 0 svg/wk: 1885 (62); 0.5-6 svg/wk: 1947 (26); ≥7 svg/wk: 2414 (38), P<0.05; - TEI: Kcal/d, mean (SE), chi-square test Soft drinks:; 0 svg/wk: 1885 (62); 0.5-6 svg/wk: 1947 (26); ≥7 svg/wk: 2414 (38), P<0.05; - Study beverage intake at baseline: Soft drinks: 11.1% 0 svg/wk, 60.8% 0.5-6 svg/wk, 28.1% ≥7 svg/wk; Excluded from Study or Analysis: lost to follow-up, those who did not complete FFQ at time 1 or time 2, had implausible energy intakes, and did not report BMI at time 1 or time 2. | Exposure: Soft drinks, punch (Hawaiian punch, lemonade, Koolaid, or other noncarbonated fruit drink). Serving size NR.; Comparator: Different intake of SSBs, categorical intake (0, 0.5-6, ≥7 servings/wk); Exposure Assessment Methods and Timing:; - Validated 149-item youth and adolescent food-frequency questionnaire (YAQ). Responses ranged from “never/less than once per month” to ≥4 glasses, cups, cans, or drinks per day depending on beverage type.; - 1998-1999 , 2003-2004; Outcomes and Assessment Methods:; - BMI calculated from self-reported height and weight. Overweight considered as BMI ≥85th percentile for sex and age; - 1998-1999 , 2003-2004 | [underlined: Change in BMI over 5y by number of servings/wk of time 2 SSB intake], kg/m2, mean (SE), multivariable linear regression; Soft drinks; Model 1; 0 svg/wk: 1.66 (0.17); 0.5-6 svg/wk: 1.92 (0.10); ≥7 svg/wk: 1.77 (0.14); P=0.36; Model 2; 0 svg/wk: 1.74 (0.18); 0.5-6 svg/wk: 1.92 (0.10); ≥7 svg/wk: 1.80 (0.15); P=0.60; Model 3; 0 svg/wk: 1.81 (0.17); 0.5-6 svg/wk: 1.93 (0.10); ≥7 svg/wk: 1.81 (0.15); P=0.73; Model 3, adjusted for dieting variables; 0 svg/wk: 1.79 (0.18); 0.5-6 svg/wk: 1.95 (0.10); ≥7 svg/wk: 1.83 (0.16); P=0.66; Punch; Model 1; 0 svg/wk: 1.93 (0.17); 0.5-6 svg/wk: 1.85 (0.09); ≥7 svg/wk: 1.74 (0.18); P=0.76; Model 2; 0 svg/wk: 2.02 (0.18); 0.5-6 svg/wk: 1.80 (0.09); ≥7 svg/wk: 1.93 (0.20); P=0.50 | Model Adjustments:; - TEI: no; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position, anthropometry at baseline, physical activity (models 2 and 3); - Other: Model 1: key confounders as listed; baseline beverage consumption of the beverage being analyzed; Model 2: all beverages assessed together in the model; adjusted for key confounders and all baseline beverages, cohort, change in BMI, baseline and time 2 strenuous physical activity, and time 2 weekday television watching and coffee and tea consumption; Model 3: soft drinks, low-calorie soft drinks and white milk assessed together in the model; adjusted for key confounders; baseline white milk, soft drink, and low-calorie drink consumption, baseline and time 2 strenuous physical activity, time 2 weekday television watching and coffee and tea consumption, and dieting and parental weight-related concerns; Limitations:; - Did not account for key confounders: diet quality; - No preregistered data analysis plan; No information on non-completers; Lack of accurate assessment of exposure portion sizes; Funding:; HHS (Maternal and Child Health Bureau, Health Resources and Services Administration)
Viner, 2006^93^; PCS, 1970 British Birth Cohort, UK; Analytic N=4,461; Included in meta-analysis: No; Participant characteristics at baseline:; adolescents; - Age: ~16y; - Female: 51%; - Race/ethnicity: NR; - SEP: NR; - Anthropometry: 8.2% with BMI ≥95th percentile; - Physical activity: 44% with ≥mean frequency of sport played in school; - Diet quality: Days per week meal obtained from takeaway: 40% none, 39% 1d/wk, 13% 2d/wk, 9% 3 d/wk or more; - TEI: NR; - Study beverage intake at baseline: # carbonated drinks previous day: zero, 57%; one, 31%; ≥2, 12%; Excluded from Study or Analysis: Missing data on exposure or covariates (baseline) or outcome (baseline or follow-up) | Exposure: Nonalcoholic carbonated drinks; Comparator: Categorical intake, # drinks in previous day: 0, 1, ≥2; Exposure Assessment Methods and Timing:; - Self-report: participants asked how many nonalcoholic carbonated drinks they consumed the day before completing questionnaire, unclear if validated; - Baseline; Outcomes and Assessment Methods:; - Height and weight at 16y were measured by school medical staff, and was self-reported at 30y. BMI z-score at 16y calculated using UK 1990 growth reference, and at 30y was calculated separately for each sex from the cohort mean (SD) using self-reported data.; - Baseline (16y), followup (30y) | [underlined: Change in BMI z-score by # carbonated drinks in previous day], β (SE), linear regression; 0 drinks (REF); 1 drink: 0.05 (−0.03, 0.13), P=0.2; ≥2 drinks: 0.13 (0.01, 0.26), P=0.04 | Model Adjustments:; - TEI: no; - Key confounders: sex, age, socioeconomic position, anthropometry at baseline; - Other:; Limitations:; - Did not account for key confounders: race and/or ethnicity, physical activity, diet quality; - Exposure not well defined; Exposure data only measured at baseline; No information on non-completers; Height and weight were self-reported at outcome; No preregistered data analysis plan; Funding:; NR
Vinke, 2020^94^; PCS, Groningen Expert Center for Kids with Obesity (GECKO) Drenthe Birth Cohort, The Netherlands; Analytic N=1,257; Included in meta-analysis: Yes; Participant characteristics at baseline:; Birth cohort (2006-2007) examining the determinants and development of childhood overweight in Dutch children; - Age: 5.8 (0.3)y at BMI measure, 6.0 (0.3)y at FPQ; - Female: 50%; - Race/ethnicity: 6.0% ethnic minorities in larger cohort; - SEP: Maternal education: 28.3% Low, 31.4% Middle, 40.3% High; Paternal education: 38.6% Low, 27.5% Middle, 33.9% High; - Anthropometry: BMI z-score Mean (SD): 0.3 (0.8); Overweight/obesity: 10.5%; - Physical activity: NR; - Diet quality: NR; - TEI: NR; - Study beverage intake at baseline: SSB frequency at baseline, Mean: 3.1/d, Q1: 1.9/d, Q2: 2.7/d, Q3: 3.6/d, Q4: 4.9/d; Excluded from Study or Analysis: birth weight <2500 g; missing SSB consumption data, potential confounders, or BMI at age 5/6 or 10/11 years | Exposure: SSB (soda, fruit drinks, instant lemonade made with fruit syrup, sugar-sweetened tea, and sugar-sweetened yoghurt drinks); Comparator: Categorical intake (Quartiles); Exposure Assessment Methods and Timing:; - Non-validated Food Pattern Questionnaire (FPQ, parental report of frequency/wk); - At 5/6y; Outcomes and Assessment Methods:; - Trained nurses measured weight, height. Age- and sex-specific BMI z-score determined with Dutch National Growth Study (1997) standard. BMI z-score change was standardized to 5y period by dividing the BMI z-score change by the age interval between measurements in months, multiplied by 60. Overweight defined as BMI z-score >1.310 for boys, and >1.244 for girls. Due to few cases, obesity was included in overweight category; - At 5/6y and 11/12y | [underlined: Change in BMI z-score over 5y], Linear regression, β (95% CI); Q1: Ref; Q2: 0.122 (0.014, 0.229), p=0.027; Q3: 0.066 (−0.041, 0.174), p=0.227; Q4: 0.160 (0.050, 0.271), p=0.004; [underlined: Risk of overweight/obesity incidence at 5y follow up], Logistic regression, OR (95% CI), n=1125; Q1: Ref; Q2: 2.30 (1.15, 4.57); Q3: 2.13 (1.09, 4.17); Q4: 3.12 (1.60, 6.07); p=0.010 | Model Adjustments:; - TEI: No; - Key confounders: sex, age, socioeconomic position (parental education level), anthropometry at baseline; - Other: BMI of mother and father at birth, smoking during pregnancy, age of mother at birth; Limitations:; - Did not account for key confounders: race and/or ethnicity, physical activity, diet quality; - FPQ did not ask about portion size; No preregistered data analysis plan; Funding:; Hutchison Whampoa Ltd., Hong Kong; University of Groningen; Well Baby Clinic Foundation Icare; Noordlease; Pediatric Association of The Netherlands; and Youth Health Care Drenthe
Wang, 2022^95^; PCS, Nanjing RCT, China; Analytic N=1,633; Included in meta-analysis: Yes; Participant characteristics at baseline:; Third graders from rural or urban schools in Nanjing, eastern China; - Age: 9.36 (0.48)y; - Female: 46%; - Race/ethnicity: NR; - SEP: Parental education: 33% ≤9y, 67% >9y; - Anthropometry: Height (cm) Mean (SD): 134.15 (6.60);; Weight (kg) Mean (SD): 31.19 (7.25);; BMI Mean (SD): 17.16 (2.93);; BMI z-score Median (IQR): −0.24(−0.72, 0.58); - Physical activity: Physical activity outside school (min/wk) Mean (SD): 217.33 (221.92); - Diet quality: NR; - TEI: NR; - Study beverage intake at baseline: SSB mL/wk at baseline, Median (IQR): 750 (250, 1750); Excluded from Study or Analysis: students who did not drink any SSBs during the study | Exposure: SSB (carbonated beverages, fruit and/or vegetable beverages, sweetened tea beverages, lactobacillus milk beverages, sports and energy beverages, plant-protein beverages, brewed beverages and coffee beverages) Total SSB consumption calculated by multiplying the frequency of intake by the average amount consumed each time. Changes in SSB consumption before and after the SSB intervention categorized as Level-Up if it increased after the intervention, Level-Same if it remained unchanged, and Level-Down if it decreased; Comparator: Categorical change in SSB intake over 12mo: Level-Up (increased intake after intervention), Level-Same, Level-Down (decreased intake after intervention); Exposure Assessment Methods and Timing:; - Non-validated Questionnaire (child report of frequency/wk and amount consumed each time for each of 8 SSB categories). Total amount of SSB consumption was calculated by multiplying the frequency of intake by the average amount consumed each time; - At baseline and 12mo follow-up; Outcomes and Assessment Methods:; - Trained nurses measured children’s heights and weight, which were used to calculate BMI. Age- and sex- adjusted BMI z-scores, derived from the Chinese National Survey on Students Constitution and Health (2014); - At baseline and 12mo follow-up | [underlined: Change in BMI z-score over 12mo]; Linear regression, β (95% CI); Level-Up (n=619): (Ref); Level-Same (n=181): −0.028 (−0.100, 0.045), p=0.481; Level-Down (n=833): −0.057 (−0.103, −0.012), p=0.014 | Model Adjustments:; - TEI: No; - Key confounders: sex, age, socioeconomic position (parental education level), anthropometry at baseline, physical activity; - Other: area (rural/urban), father’s BMI, mother’s BMI, homework time, screen time, sleep time; Limitations:; - Did not account for key confounders: race and/or ethnicity, diet quality; - SSB intake was self-reported in the context of an unblinded RCT; No pre-specified analysis plan;; Funding:; Jiangsu Provincial Health Commission; Nanjing Municipal Health Commission
Welsh, 2005^96^; PCS, Missouri WIC Program, U.S.; Analytic N=10,904; Included in meta-analysis: Yes; Participant characteristics at baseline:; Children; - Age: ~34 mo; - Female: 50%; - Race/ethnicity: White: 88.6%; Black: 5.8%; Other: 5.6%; - SEP: All enrolled in Missouri WIC program; - Anthropometry: BMI %: Normal or underweight 75.5%, At risk for overweight 14.5%, Overweight 10.1%; - Physical activity: NR; - Diet quality: NR; - TEI: Mean: 1780 kcal/d; - Study beverage intake at baseline: Mean baseline intake, drinks/d; Sweet drinks: 2.9; Soda: 0.3; Fruit drinks: 0.7; Excluded from Study or Analysis: Age <2y or >3y at baseline, not enrolled in Missouri WIC Program between January 1999 and December 2001; missing values for key dietary or outcome variables at baseline or follow-up, extreme BMI values (z-score < −4 or >5); extremes in total energy intake (<800 or >3500 kcal) | Exposure: “sweet drinks”: all sugar-sweetened and naturally sweet drinks, including “vitamin C juice (orange juice or juice with vitamin C added),” “other juices,” “fruit drinks (Hi-C, Kool-Aid, lemonade),” and “soda (soda, soft drink, pop [not sugar-free]).”; Comparator: Sweet drink intake (categorical; drinks/d): 0-<1 (ref); 1-<2; 2-<3; ≥3; Exposure Assessment Methods and Timing:; - Validated FFQ completed by parents; represents usual intake in the last 4wk; - Baseline; Outcomes and Assessment Methods:; - Standing height measured using standard measuring board. Weight measured using pediatric scale or beam balance scale. Age- and sex-specific BMI percentile based on 2000 CDC growth chart. Normal or underweight (BMI<85th%), at risk for overweight (BMI 85th-<95th percentile), overweight (BMI≥95th percentile); - Baseline, 1y follow-up | [underlined: Overweight at follow up (BMI >95th%), by sweet drink intake (drinks/d) stratified by baseline weight status:] Logistic regression, OR (95% CI); Normal or underweight at baseline; 0-<1 (n=952, Ref); 1-<2 (n=2147): 1.5 (0.9, 2.4); 2-<3 (n=1737): 1.4 (0.8, 2.3); ≥3 (n=3392): 1.3 (0.8, 2.1); At risk of overweight at baseline; 0-<1 (n=188, Ref); 1-<2 (n=432): 2.0 (1.3, 3.2); 2-<3 (n=328): 2.0 (1.2, 3.2); ≥3 (n=631): 1.8 (1.1, 2.1); Overweight at baseline; 0-<1 (n=124), Ref; 1-<2 (n=312): 2.1 (1.3, 3.4); 2-<3 (n=204): 2.2 (1.4, 3.7); ≥3 (n=457): 1.8 (1.1, 2.9); Data on sweet drinks excluding sodas available in Table 4 of paper (includes fruit drinks, vitamin C-containing juices and other juices) | Model Adjustments:; - TEI: yes; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position, anthropometry at baseline, diet quality (sweet food intake, high-fat food intake); - Other:; Limitations:; - Did not account for key confounders: physical activity; - Exposure data only measured at baseline; Attrition rate unclear, but may be >70%; No preregistered data analysis plan; Funding:; NR
Wheaton, 2015^97^; PCS, Longitudinal Study of Australian Children (LSAC), Australia; Analytic N=4,169; Included in meta-analysis: No; Participant characteristics at baseline:; Children; - Age: 4.8 (0.2)y; - Female: 49%; - Race/ethnicity: 96% born in Australia; - SEP: disadvantaged areas “underrepresented”; - Anthropometry: Mean (SD) BMI z-score: 0.66 (0.99); Weight status: Thinness/normal weight 68%, with overweight 23%, with obesity 9%; - Physical activity: NR; - Diet quality: NR; - TEI: NR; - Study beverage intake at baseline: NR; Excluded from Study or Analysis:; missing data | Exposure: fruit juice; non-diet soft drink or cordial; Comparator: Categorical intake: 0=Normal to normal (ref), 1=Normal to with overweight/obesity, 2=with overweight/obesity to with overweight/obesity, 3= With overweight/obesity to normal; Exposure Assessment Methods and Timing:; - Parent-report survey questions; represents intake during previous 24hr; - At wave 1 (age 4-5y), and biennial waves 2 and 3 (age 6-8y, 8-9y); Outcomes and Assessment Methods:; - Weight measured to nearest 50 g using Salter Australia bathroom scales; Height measured twice to nearest 0.1 cm using portable rigid stadiometer; Age- and sexspecific BMI z-score calculated according to WHO Growth Standard for children from birth-60mo. Weight status categories based on WHO cut-off points: with overweight (BMI >25 kg/m2), with obesity (BMI>30 kg/m2); - At wave 1 (age 4-5y), and biennial waves 2-4 (age 6-8y, 8-9y,10-11y) | [underlined: Change in Weight Status] (WHO BMI z-score cut off points), Logistic regression, RRR (SE); Wave 1 (age 4-5y) to Wave 2 (age 6-7y); 0 (normal to normal; ref) versus; 1 (normal to with overweight/obesity): 0.95 (0.07), P=0.52; 2 (with overweight/obesity to with overweight/obesity): 1.05 (0.05), P=0.28; 3 (with overweight/obesity to normal): 1.04 (0.06), P=0.51; Wave 1 (age 4-5y) to Wave 3 (age 8-9y); 0 (normal to normal; ref) versus; 1 (normal to with overweight/obesity): 0.97 (0.06), P=0.58; 2 (with overweight/obesity to with overweight/obesity): 1.09 (0.05), P=0.07; 3 (with overweight/obesity to normal): 0.95 (0.06), P=0.40; Wave 1 (age 4-5y) to Wave 4 (10-11y); 0 (normal to normal; ref) versus; 1 (normal to with overweight/obesity): 0.97 (0.05), P=0.57; 2 (with overweight/obesity to with overweight/obesity): 1.13 (0.06), P=0.01; 3 (with overweight/obesity to normal): 0.93 (0.06), P=0.21 | Model Adjustments:; - TEI: yes; - Key confounders: sex, age, race/ethnicity, socioeconomic position, anthropometry at baseline, diet quality (fruit and vegetable intake, high-fat food intake); - Other: Mother’s and father’s BMI; Limitations:; - Did not account for key confounders: physical activity; - Exposure data collection tool not validated, Unclear if % missing data was equal across exposure groups,; No preregistered data analysis plan; Funding:; Australian National Health and Medical Research Council; Australian National Heart Foundation; NIH; National Health and Medical Research Council Centre for Research Excellence in Obesity Policy and Food Systems; Deakin University
Whetstone, 2012^98^; PCS, North Carolina Health and Wellness Trust Fund programs (NRCT), U.S.; Analytic N=1,144; Included in meta-analysis: No; Participant characteristics at baseline:; Children; - Age: 9.5 (4.1)y; - Female: 52%; - Race/ethnicity: White 64.7%; African-American 35.3%, ; Hispanic/Latino origin 2.6%,; - SEP: NR; - Anthropometry: BMI z-score: 0.82 (1.13); Weight status: underweight=1.6%, healthy weight=55.0%, overweight=16.9%, obesity=26.6%; - Physical activity: Mean number of days of exercise or physical activity per week: 4.49; - Diet quality: NR; - TEI: NR; - Study beverage intake at baseline: 39.6% did not drink soda at baseline; 31.1% drank a sweetened beverage ≥3 times on a typical day; Excluded from Study or Analysis: missing height, weight, sex or race data | Exposure: Soda and sweetened beverages (no other details provided); Comparator: Continuous intake; Exposure Assessment Methods and Timing:; - Unvalidated health survey completed by parents (if child was grade K-5) or self (if child was grade 6-12); - At baseline and every 6 months during follow-up period; average follow-up 20.5mo (range: 8-29mo); Outcomes and Assessment Methods:; - Height measured by trained staff, stadiometers recommended but alternative instructions for triangular ruler and metal tape measure provided; Weight measured by trained staff using balance beam or digital scale. BMI z-score (BMI z-score) calculated using approach on CDC website. Weight status were age- and gender-specific CDC designations: underweight (BMI<5%), healthy weight (5%≤BMI<85%), with overweight (85%≤BMI<95%), with obesity (BMI≥95%); - At baseline and every 6 months during follow-up period; average follow-up 20.5y (range: 8-29mo) | [underlined: Weight Status, Percentage of children with overweight/obesity who lowered their weight status category] (subgroup n NR), Chi-square difference; Decreased soda intake versus. did not decrease soda intake: 30.6% versus 22.2%; [underlined: BMI z-score, Change in BMI z-score among children with overweight/obesity] (subgroup n NR), ANOVA; Decreased soda intake versus. did not decrease soda intake: −0.20 versus −0.09, p=0.038 | Model Adjustments:; - TEI: no; - Key confounders: Sex, age, race and/or ethnicity, anthropometry at baseline; - Other:; Limitations:; - Did not account for key confounders: SEP, physical activity, diet quality; - Exposure not clearly defined; tool not validated; Subgroup analyses reported; Results from full sample NR; no preregistered data analysis plan; Funding:; North Carolina Health and Wellness Trust Fund Commission
Wijga, 2010^99^; PCS, Dutch Prevention and Incidence of Asthma and Mite Allergy (PIAMA) birth cohort, Netherlands; Analytic N=2,214; Included in meta-analysis: No; Participant characteristics at baseline:; children; - Age: ~5y; - Female: 48%; - Race/ethnicity: NR; - SEP: Maternal education: Low (primary, lower vocational, lower general), 23.6%; Intermediate (senior high school and intermediate vocational), 41.7%; High (higher vocational and university), 34.8%; - Anthropometry: NR; - Physical activity: Member of a sport club: 61.6%; Walking/cycling to school, Never: 36.6%, <0.5 hr/d: 53.1%, ≥0.5hr/d: 10.3% Playing outside: 4.5% ≤ once/wk; 22.8% 1-3 times/wk, 72.7% >3 times/wk; - Diet quality: Fast food consumption: 36% low (median 125 kcal/wk), 40% intermediate (370 kcal/wk), 24% high (620 kcal/wk); Snack consumption: 33.2% low (median 539 kcal/wk), 33.5% intermediate (801 kcal/wk), 33.4% high (1219 kcal/wk); - TEI: NR; - Study beverage intake at baseline: Soft drink consumption at 5y:; Low (median 343 kcal/wk): 34%; Intermediate (median 493 kal/wk): 34%; High (749 kcal/wk): 32%; Excluded from Study or Analysis: NR | Exposure: Soft drinks (details NR); Comparator: Continuous intake, kJ/wk; categorical intake, by maternal education status (high/intermediate versus. low) and maternal overweight status (BMI <25 kg/m2 versus. BMI ≥25 kg/m2); Exposure Assessment Methods and Timing:; - FFQ on reported frequencies of consumption of 4 types of soft drinks (details NR); - 5y, 7y; Outcomes and Assessment Methods:; - Weight (nearest 0.1 kg) and height (nearest 0.1 cm) measured by trained research staff using calibrated measuring equipment; BMI calculated as kg/m2. Overweight and obesity defined according to age and gender-specific international standards; - 8y | [underlined: Overweight/obesity at age 8y], OR (95% CI), logistic regression; Model 3 (not adjusted for maternal overweight): 0.92 (0.46, 1.86); Model 4 (not adjusted for low maternal education): 0.91 (0.44, 1.88); [underlined: Overweight/obesity at age 8y by maternal education status], OR (95% CI), logistic regression; High/intermediate maternal education: 0.92 (0.41, 2.07); Low maternal education: 0.93 (0.33, 2.64); [underlined: Overweight/obesity at age 8y by maternal overweight status], OR (95% CI), logistic regression; Maternal BMI < 25.0 kg/m2: 0.66 (0.27, 1.63); Maternal BMI ≥25.0 kg/m2: 1.49 (0.54, 4.06) | Model Adjustments:; - TEI: no; - Key confounders: sex, age, socioeconomic position, physical activity, diet quality (fast food consumption; snack consumption); - Other: Birth weight; breastfeeding; maternal overweight; screen time; Limitations:; - Did not account for key confounders: race and/or ethnicity, anthropometry at baseline; - Exposure not well defined; Exposure data only measured at baseline; No preregistered data analysis plan; Funding:; NR
Yiotaldiotariotam, 2013^102^; PCS, Secondary analysis of Dutch Obesity Intervention in Teenagers (DOiT), The Netherlands; Analytic N=1,108; Included in meta-analysis: Yes; Participant characteristics at baseline:; adolescents participating in an 8mo school-based behavioral intervention; - Age: ~12.7y; - Female: 50%; - Race/ethnicity: 12% non-Western immigrants; - SEP: NR; - Anthropometry: BMI ~18.3 kg/m2; 14% overweight/obesity; - Physical activity: ~30 min/d active transport to/from school; - Diet quality: ~1.54 portions/d of high-calorie snacks; - TEI: NR; - Study beverage intake at baseline: ~0.94 L/d SSB; ~0.68 L/d soft drinks; ~0.20 L/d fruit juice; Excluded from Study or Analysis: Non-Western immigrants born outside Netherlands but in Europe, or in North America, Oceania, Indonesia, Japan; | Exposure: Sugar-containing beverages; Soft drinks (fizzy drinks not including “diet” drinks, lemonade, ice tea, energy drinks); Fruit juices (unclear if 100%); Comparator: continuous (L/d); Exposure Assessment Methods and Timing:; - Validated questionnaire; - At baseline, 8, 12, and 20mo; Outcomes and Assessment Methods:; - Weight and height were measured and used to calculate BMI. WC and skinfold thickness (triceps, biceps, subscapular, suprailiac) were measured; - At baseline, 8, 12, and 20mo | [underlined: WC] (cm), β (95% CI), parallel process latent growth model; SSB: 0.06 (−0.07, 0.19); Soft drinks: 0.07 (−0.11, 0.24); Fruit juice: 0.09 (−0.29, 0.50); [underlined: Sum of skinfolds] (mm), β (95% CI), parallel process latent growth model; SSB: 0.002 (−0.56, 0.61); Soft drinks: 0.02 (−0.62, 0.77); Fruit juice: 0.15 (−1.19, 1.53); [underlined: BMI] (kg/m2), β (95% CI), parallel process latent growth model; SSB: 0.10 (0.01, 0.13); Soft drinks: 0.15 (−0.25, 0.32); Fruit juice: 0.23 (0.06, 0.43); (Positive regression coefficient indicates that a decrease in SSB and fruit juice consumption led to decrease in BMI) | Model Adjustments:; - TEI: no; - Key confounders: sex, age, anthropometry at baseline; - Other: N/A; Limitations:; - Did not account for key confounders: race and/or ethnicity, socioeconomic position,physical activity, diet quality; - No information on non-completers; No preregistered data analysis plan; Funding:; World Cancer Research Fund; Netherlands Heart Foundation; Netherlands Organization for Health Research and Development; EMGO Institute
Yoon, 2022^103^; PCS, Growth and Obesity Cohort Study (GOCS), Chile; Analytic N=374; Included in meta-analysis: No; Participant characteristics at baseline:; Adolescent girls; - Age: ~10-11y at first exposure assessment (2013); - Female: 100%; - Race/ethnicity: NR, though in the Discussion they note the “relatively homogenous racial/ethnic makeup of the cohort”; - SEP: Maternal Education: 19% less than high school, 64% high school, 16% university; - Anthropometry: Mean (SD); BMI Z-score: 0.8 (1.1); Fat %: 27 (5.3)% WC: 72.5 (9.6) cm; - Physical activity: NR; - Diet quality: Meat intake, mean (SD): 86 (56) g/day; Dairy intake, mean (SD): 226 (160), g/day; - TEI: Mean (SD): 1874 (546) kcal/d; - Study beverage intake at baseline: Mean (SD): 342 (210) mL (~12oz/d); Quartile intake, mL/d:; Q1: 100; Q2: 253; Q3: 376; Q4: 626; Excluded from Study or Analysis: born before 2002 or after 2003 (< 2.6y or >4y in 2006); not attending a low- or middle-low-income nursery belonging to the National Association of Dare Care Centers (JUNJI) in 2006; no evidence of prior year enrollment in a JUNJI center; pre-term (<37wk), non-singleton birth; birth weight ≤ 2500gmissing follow-up data through Tanner stage 4 or 5; missing breast composition measurements; no prospective dietary data; physical and psychological conditions affecting growth (e.g., skin burns, brain tumor, hyperthyroidism) | Exposure: Any beverage with added sugar including favored water, energy and sport drinks, full-sugar (i.e., non-diet) sodas, fruit and vegetable juice drinks with added sugar, coffee and tea with added sugar, dairy-based beverages and dairy substitutes with added sugar, and powdered drinks with added sugar (e.g., Nesquik chocolate).; Comparator: Categorical intake, by quartiles (mean intake):; Q1 (n=88): 100 mL/d; Q2 (n=99): 253 mL/d; Q3 (n=92): 376 mL/d; Q4 (n=95): 626 mL/d; Exposure Assessment Methods and Timing:; - 24-hr recalls collected by dietitians using USDA multiple-pass method. 79% were collected on a weekday, 17%, on a weekend, and 4%, on a holiday. SSB intake (in mL/day) was averaged over follow-up period. Mean=2.5 recalls per participant.; - Biannually from 2013 to 2015; Outcomes and Assessment Methods:; - Weight, height, WC assessed by study staff. BMI calculated and age- and sex-standardized (WHO Child Growth Reference (2007)); - Twice/year from 2011 onward, to Tanner stage 4 or 5 | [underlined: BMI z-score], β (95% CI), linear regression; Q1: ref; Q2: 0.16 (−0.17, 0.49); Q3: 0.09 (−0.25, 0.43); Q4: 0.01 (−0.32, 0.35); P=0.82; [underlined: Body fat percentage], β (95% CI), linear regression; Q1: ref; Q2: 1.19 (−0.41, 2.8); Q3: 0.45 (−1.22, 2.12); Q4: −0.21 (−1.86, 1.43); P=0.44; [underlined: Waist circumference], β (95% CI), linear regression; Q1: ref; Q2: 1.45 (−1.51, 4.4); Q3: 0.85 (−2.22, 3.93); Q4: −0.23 (−3.26, 2.81); P=0.69 | Model Adjustments:; - TEI: yes; - Key confounders: sex, age, socioeconomic position (maternal education); - Other: Hours of daily television watching after school, dairy intake, meat intake; Limitations:; - Did not account for key confounders: race and/or ethnicity, anthropometry at baseline, physical activity, diet quality; - No preregistered data analysis plan; Funding:; NCI/NIH, NIEHS, Chilean National Science Council
Zhang, 2020^104^; PCS, Children of 1997, China; Analytic N=2617; Included in meta-analysis: Yes; Participant characteristics at baseline:; adolescents; - Age: 13y; - Female: 51%; - Race/ethnicity: All born in Hong Kong; - SEP: Highest parental education: 28% ≤grade 9; 43% grade 10-11; 29% ≥grade 12; Household income (n=3213 with data): 18% first 1st quintile; 19% 2nd; 20% 3rd; 21% 4th; 22% 5th quintile ; Highest parental occupation (n=3158 with data): 27% professional; 15% managerial; 29% non-manual skilled; 16% manual skilled; 10% semi-skilled; 3% unskilled; - Anthropometry: BMI z-score at 13y: ~0.11; BMI at 13y: ~19.8 kg/m2; - Physical activity: at 11y (n=3225 with data): 71% < 1hr/day; - Diet quality: Fruit consumption at 11y: 4% < weekly; 27% 1-3 times/wk; 18% 4-6 times/wk; 51% ≥daily; Vegetable consumption at 11y: 2% < weekly; 9% 1-3 times/wk; 11% 4-6 times/wk; 78% ≥daily; Meat consumption at 11y (n=2713 3607 with data): 33 1% < weekly; 47 12% 1-3 times/wk; 11 18% 4-6 times/wk; 8 68% ≥daily; - TEI: NR; - Study beverage intake at baseline: SSB intake at 13y (n=2713 with data): 33% < weekly; 47% 1-3 times/wk; 11% 4-6 times/wk; 8% ≥daily; Excluded from Study or Analysis: born before 4/1/1997 or after 5/31/1997; not born in Hong Kong; missing information on exposure, outcome or confounders (complete case analysis) | Exposure: Included beverages sweetened with sugar and beverages sweetened with LNCSB.; Comparator: Categorical intake: < weekly, 1-3 times/wk, 4-6 times/wk, ≥daily; Exposure Assessment Methods and Timing:; - FFQ (not validated for SSB consumption), single question asking about consumption of canned pop/soda/soft drinks in past week.; - 13y (2010); Outcomes and Assessment Methods:; - Height, weight, WC, hip circumference and body fat percentage measured by study staff. Weight and body fat percentage assessed by bioelectrical impedance (BIA); WC and hip circumference measured using standard protocol. Age and sex-specific BMIz derived from 2007 WHO growth reference. Overweight and obesity defined using 2000 IOTF cut-offs (equivalent to adult BMI of ≥25 to <30, ≥30 kg/m2, respectively.; - WC, WHR, body fat percentage: 16-19y (2013-2016); BMIz, Overweight/Obesity: 14-18y | [underlined: BMI z-score], β (95% CI), general estimating equation, n=2617; < weekly: ref; 1-3 times/wk: −0.04 (−0.13, 0.06); 4-6 times/wk: 0.04 (−0.11, 0.18); ≥Daily: 0.00 (−0.18, 0.18); [underlined: WC], β (95% CI), multivariable linear regression, n=1453; < weekly: ref; 1-3 times/wk: 0.11 (−0.89, 1.11); 4-6 times/wk: 0.17 (−1.40, 1.74); ≥Daily: 0.89 (−0.93, 2.71); [underlined: Waist-to-hip ratio], β (95% CI), multivariable linear regression, n=1448; < weekly: ref; 1-3 times/wk: 0.000 (−0.006, 0.006); 4-6 times/wk: 0.001 (−0.009, 0.010); ≥Daily: 0.005 (−0.006, 0.016); [underlined: Body fat percentage], β (95% CI), multivariable linear regression, n=1452; < weekly: ref; 1-3 times/wk: 0.20 (−0.50, 0.91); 4-6 times/wk: 0.41 (−0.68, 1.51); ≥Daily: 0.90 (−0.37, 2.17); [underlined: Risk of overweight] (including obesity), OR (95% CI), general estimating equation, n=2617; < weekly: ref; 1-3 times/wk: −0.08 (−0.32, 0.16); 4-6 times/wk: −0.15 (−0.53, 0.24); ≥Daily: −0.19 (−0.64, 0.27) | Model Adjustments:; - TEI: no; - Key confounders: sex, age, socioeconomic position (parental highest education, parental highest occupation, household income per head); - Other: maternal age at birth, maternal birthplace, interaction of maternal birthplace with parental highest education level; Limitations:; - Did not account for key confounders: race and/or ethnicity, anthropometry at baseline, physical activity, diet quality; - Not sufficiently powered; Selection into study related to exposure and outcomes (complete case analysis); Exposure assessment tool not validated and may include LNCSB; Selection of reported results; High attrition; No preregistered data analysis plan; Funding:; Government of the Hong Kong SAR, WYNG Foundation
Zheng, 2014^109^; PCS, European Youth Heart Study (EYHS), Denmark; Analytic N=187 (6y follow-up); 283 (12y follow-up); Included in meta-analysis: Yes; Participant characteristics at baseline: school children in Odense, Denmark; - Age: ~9.6y; - Female: 56%; - Race/ethnicity: NR; - SEP: 57% Low (elementary, high school, or vocational education); - Anthropometry: BMI ~17.3 kg/m2; - Physical activity: 55% Active (regular exercise); - Diet quality: NR; - TEI: at 9y: ~9.5 MJ/d at 15y: 10.3 MJ/d; - Study beverage intake at baseline: at 9y: 47% Non-consumer, 40% ≤1 svg/d, 13% >1 svg/d; at 15y: 50% Non-consumer, 24% ≤1 svg/d, 26% >1 serv/d; A higher proportion of boys than girls consumed SSB at 1st follow up (age 15y, P=0.003); Excluded from Study or Analysis: incomplete information on anthropometrics and dietary intake or who underreported TEI | Exposure: SSB intake (regular soft drinks, fruit drinks, and cordials sweetened with caloric sweeteners); Comparator: Categorical intake: Non-consumer, ≤1, >1 svg/d; 1 svg=12 oz No change, decrease, increase; Exposure Assessment Methods and Timing:; - One 24h recall face-to-face interview supplemented with parent-assisted food record; represents food intake; - Baseline (age 9), 6y follow-up (age 15); Outcomes and Assessment Methods:; - Height measured bare feet to nearest 5mm using stadiometer. Weight measured to nearest 0.1 kg using beam balance scale. BMI calculated as kg/m2. Waist circumference (WC) measured twice with metal anthropometric tape (mean was used). Sum of 4 skinfolds (Σ4SF) obtained by adding average skinfolds of 4 sites (biceps, triceps, subscapular, and suprailiac) that were measured in duplicate with Harpenden fat calipers; - Baseline (age 9), 6y follow-up (age 15), 12y follow-up (age 21) | [underlined: WC], cm, Linear regression, β (SE); Change from 9–21y with SSB intake at 9y; None (n=134, ref) versus; ≤1 svg/d (n=112): 0.98 (1.3), P=0.46; >1 svg/d (n=37): 0.80 (2.02), P=0.69; Change from 15–21y with SSB intake at 15y; None (n=94, ref) versus; ≤1 svg/d (n=43): 2.58 (1.50), P=0.09; >1 svg/d (n=50): 2.72 (1.51), P=0.07; Change from 15–21y with SSB intake at 15y (NOT adjusted for TEI); None (n=94, ref) versus; ≤1 svg/d (n=43): 2.57 (1.49), P=0.09; >1 svg/d (n=50): 2.69 (1.45), P=0.04; Change from 15–21y with change in SSB intake from 9-15y; No change (n=45, ref) versus; Decrease (n=64): 0.83 (1.61), P=0.75; Increase (n=78): 3.25 (1.53), P=0.07; Change from 15–21y with change in SSB intake from 9-15y (NOT adjusted for TEI); No change (n=45, ref) versus; Decrease (n=64): 0.87 (1.55), P=0.57; Increase (n=78): 2.72 (1.53), P=0.04; [underlined: Σ4SF], mm, Linear regression, β (SE); Change from 9–21y with SSB intake at 9y; None (n=134, ref) versus; ≤1 svg/d (n=112): 0.76 (5.68), P=0.79; >1 svg/d (n=37): 0.98 (3.63), P=0.79; Change from 15–21y with SSB intake at 15y; None (n=94, ref) versus; ≤1 svg/d (n=43): 1.37 (3.94), P=0.73; >1 svg/d (n=50): 2.95 (3.92), P=0.45; Change from 15–21y with change in SSB intake from 9-15y; No change (n=45, ref) versus; Decrease (n=64): 4.03 (4.09), P=0.33; Increase (n=78): 4.60 (4.09), P=0.26; Sum of skinfold data were also NS when TEI was not adjusted for; [underlined: BMI], kg/m2, Linear regression, β (SE); Change from 9–21y with SSB intake at 9y; None (n=134, ref) versus; ≤1 svg/d (n=112): 0.53 (0.55), P=0.34; >1 svg/d (n=37): 1.42 (0.68), P=0.29; Change from 15–21y with SSB intake at 15y; None (n=94, ref) versus; ≤1 svg/d (n=43): 0.69 (0.57), P=0.23; >1 svg/d (n=50): 0.97 (0.56), P=0.09; Change from 15–21y with SSB intake at 15y; (NOT adjusted for TEI); None (n=94, ref) versus; ≤1 svg/d (n=43): 0.66 (0.56), P=0.24; >1 svg/d (n=50): 0.92 (0.54), P=0.046; Change in BMI from 15–21y with change in SSB intake from 9-15y; No change (n=45, ref) versus; Decrease (n=64): 0.38 (0.61), P=0.53; Increase (n=78): 1.00 (0.59), P=0.11; Change from 15–21y with change in SSB intake from 9-15y (NOT adjusted for TEI); No change (n=45, ref) versus; Decrease (n=64): 0.38 (0.59), P=0.51; Increase (n=78): 0.91 (0.57), P=0.09 | Model Adjustments:; - TEI: yes and no; - Key confounders: Sex, age, SEP (maternal education), anthropometry at baseline (BMI/WC/Σ4SF), physical activity; - Other: Pubertal status, baseline SSB intake (model examining change in SSB intake 9-15y ONLY); Limitations:; - Did not account for key confounders: Race and/or ethnicity, diet quality; - No preregistered data analysis plan; Funding:; NR
Zheng, 2015a^105^; PCS, Childhood Asthma Prevention Study (RCT), Australia; Analytic N=158; Included in meta-analysis: Yes; Participant characteristics at baseline:; Children; - Age: ~8y; - Female: 48%; - Race/ethnicity: Mother born in Australia/New Zealand ~78%; Father born in Australia/New Zealand ~73%; - SEP: Maternal education level >12y ~55%; Paternal education level >12y ~58%; Living in disadvantaged area ~20%; - Anthropometry: BMI z-score, Mean (SD): 0.4(1.0); Overweight/obesity: 27.2%; - Physical activity: NR; - Diet quality: NR; - TEI: Mean ~8.0 MJ/d (~1,912 kcal/d); - Study beverage intake at baseline: Median: ~210 g/d; Excluded from Study or Analysis: incomplete diet data, misreporting of energy intake, missing anthropometric data | Exposure: regular soft drinks, fruit drinks, cordials, and sugar-sweetened sport drinks; Comparator: Continuous intake, 100g/d; Exposure Assessment Methods and Timing:; - Three 24-hr dietary recalls via phone using multiple pass approach completed by children with parental assistance; Represents usual dietary intake on nonconsecutive weekdays and weekends; - At 1y follow-up (age 9y); Outcomes and Assessment Methods:; - Weight measured to nearest 0.1kg. Height measured using stadiometer. Age- and sex-specific BMI z-scores (BMI z-score) calculated using 2000 CDC growth charts. Percentage body fat measured by bioimpedance analysis.; - Baseline (age 8y), and 3.5y follow-up (age 11.5y) | [underlined: BMI z-score,] Linear regression; Change per 100 g/d increase, β (SE):; TEI unadj: 0.08 (0.03), P=0.02; TEI adj: 0.10 (0.03), P=0.003; Change per quartile (dose response):; P for trend=0.01; [underlined: % Body Fat], Linear regression; Change per 100 g/d increase, β (SE):; Bev EI unadj: 0.92 (0.31), P=0.004; Bev EI adj: 1.04 (0.32), P=0.001; Change per quartile (dose response):; P for trend=0.005 | Model Adjustments:; - TEI: yes and no; - Key confounders: Sex, age, SEP (socioeconomic index for area score, parental education level), anthropometry at baseline (BMI-z); - Other: Maternal age at birth, presence of gestational diabetes, exclusive breastfeeding at 3mo, pubertal status, randomization group (omega-3 fatty acid dietary supplementation and house dust mite reduction); Limitations:; - Did not account for key confounders: Race and/or ethnicity, physical activity, diet quality; - Exposure measured at baseline only; Baseline data for exposure and outcome occurred 1 year apart; Funding:; National Health and Medical Research Council of Australia; Cooperative Research Centre for Asthma; New South Wales Department of Health; Children’s Hospital Westmead
Zheng, 2015b^106^; PCS, Healthy Start Study (RCT), Denmark; Analytic N=352; Included in meta-analysis: Yes; Participant characteristics at baseline:; Children; - Age: 4.1y (1.1); - Female: 45%; - Race/ethnicity: NR; - SEP: Maternal education level, Tertiary or above: 78.0%; Paternal education level, Tertiary or above: 61.0%; ; Parents divorced 5.6%; - Anthropometry: Mean (SD), Body weight (kg): 18.0 (3.3); BMI z-score: 0.3 (0.9); - Physical activity: High: 59.2%; - Diet quality: NR; - TEI: Mean (SD): 4.97mJ/d (0.95) (~1,195 kcal/d); - Study beverage intake at baseline: SSB, g/d, Mean (SD):; 92 (107); Excluded from Study or Analysis: Mis-reported energy intake, incomplete diet data | Exposure: sugary drinks (sugar-sweetened carbonated and fruit-flavoured drinks and fruit juice); Comparator: Continuous intake; Exposure Assessment Methods and Timing:; - 4-d dietary record completed by parents; represents dietary intake on both weekdays and weekends; - Baseline, 1.5y follow up; Outcomes and Assessment Methods:; - Height measured using stature meter; - Weight measured using mechanical weight or beam-scale; - Age- and sex-specific BMI z-scores (BMI z-score) calculated using Lambda-Mu-Sigma method; - Baseline, 1.5y follow up | Nutrient Residual Model (includes beverage intake residuals and total energy intake); [underlined: BMI z-score,] Linear regression; Change per 100 g/d increase:; β: 0.05, SE: 0.03, P=0.10; [underlined: Body weight,] Linear regression; Change per 100 g/d increase:; β: 0.10, SE: 0.07, P=0.08; Energy Partition Model (includes absolute amount of individual beverage intake and energy from non-beverage sources); [underlined: BMI z-score,] Linear regression; Change per 100 g/d increase:; β: 0.06, SE: 0.03, P=0.04; [underlined: Body weight,] Linear regression; Change per 100 g/d increase:; β: 0.10, SE: 0.07, P=0.05 | Model Adjustments:; - TEI: yes; - Key confounders: Sex, age, SEP, anthropometry at baseline, physical activity, diet quality (other beverages); - Other: Intervention allocation, parents divorced, number of siblings living with the child, maternal pre-pregnancy overweight; Limitations:; - Did not account for key confounders: Race and/or ethnicity; - No information on non-completers; No preregistered data analysis plan; Funding:; No funding received
Zheng, 2015c^108^; PCS, European Youth Heart Study (EYHS), Denmark; Analytic N=358; Included in meta-analysis: Yes; Participant characteristics at baseline:; Children; - Age: 9.6y (0.4); - Female: 56%; - Race/ethnicity: NR; - SEP: Maternal education: 47% Low (elementary, high school, or vocational education); - Anthropometry: BMI 17.2 (2.3) kg/m2; BMI z-score 0.4 (1.1); - Physical activity: 55% Active (regular exercise); - Diet quality: NR; - TEI: Mean: 9.1 (2.3) MJ/d; - Study beverage intake at baseline: SSB, g/d, Mean (SD):; 154 (205); Excluded from Study or Analysis: incomplete diet or anthropometric data; underreporting energy intake | Exposure: regular soft drinks, lemonade, or fruit-flavored drinks; Comparator: Continuous intake, 100g/d; Exposure Assessment Methods and Timing:; - One 24h recall face-to-face interview supplemented with parent-assisted food record; represents food intake; - Baseline (age 9); Outcomes and Assessment Methods:; - Height measured bare feet to nearest 5mm using stadiometer. Weight measured to nearest 0.1 kg using beam balance scale. BMI calculated as kg/m2. Age- and sex-specific BMI z-score (BMI z-score) generated using the least mean squares method. Waist circumference (WC) measured twice with metal anthropometric tape (mean was used). Sum of 4 skinfolds (Σ4SF) obtained by adding average skinfolds of 4 sites (biceps, triceps, subscapular, and suprailiac) that were measured in duplicate with Harpenden fat calipers; - Baseline, 6y follow up | Base Model (Model 1 in paper) adjusted for confounders listed to the right, but did not adjust for TEI; Standard Multivariate Model (Model 2 in paper) adjusted for TEI; Energy Partition Model (Model 3 in paper) included energy-containing beverages only (ie, excluded water) and adjusted for energy from non-beverage sources.; [underlined: Change in WC age 9-15y: Per 100 g/d increase,] Linear regression, β (SE) (n=314); Base Model: 0.22 (0.15), P=0.14; TEI adjusted: 0.30 (0.15), P=0.18; Energy Partition: 0.25 (0.15), P=0.09; [underlined: Change in Σ4SF age 9-15y: mm, Per 100 g/d increase,] Linear regression, β (SE) (n=308); Base Model: 0.86 (0.37), P=0.02; Standard Model: 0.94 (0.39), P=0.06; Energy Partition: 0.88 (0.37), P=0.02; [underlined: Change in BMI age 9-15y: kg/m2, Per 100 g/d increase,] Linear regression, β (SE) (n=314); Base Model: 0.05 (0.02), P=0.02; TEI adjusted: 0.05 (0.02), P=0.06; Energy Partition: 0.05 (0.02), P=0.01 | Model Adjustments:; - TEI: yes and no; - Key confounders: Sex, age, SEP (maternal education), anthropometry at baseline (BMIz or WC), physical activity, diet quality (other beverages); - Other: Pubertal status, Sex x SEP, energy from non-beverage sources; Limitations:; - Did not account for key confounders: Race and/or ethnicity; - Exposure measured at baseline only; No preregistered data analysis plan; Funding:; NR
Zheng, 2019^107^; PCS, Raine Study Generation 2 (Offspring from the Western Australian Pregnancy Cohort (Raine) Study), Australia; Analytic N=667; Included in meta-analysis: Yes; Participant characteristics at baseline:; adolescents; - Age: 14y; - Female: 52%; - Race/ethnicity: NR; - SEP: Maternal Education: 70% high (≥10y of education); Family Income (quartiles, 0 being lowest): 0: 25%; 1: 30%; 2: 24%; 3: 22%; - Anthropometry: BMI: ~21 kg/m2 WC: ~75 cm; With overweight or obesity: 13%; - Physical activity: Low active (lowest tertile of PA): 42%; Active (highest 2 tertiles): 58%; - Diet quality: Healthy dietary pattern z-score: ~0.1; Western dietary pattern z-score: ~-0.3; - TEI: ~9 MJ/d; - Study beverage intake at baseline: 6% non-consumer, 54% ≤1 svg/d (mean intake: 116 g/d), 40% >1 svg/d (mean intake: 527 g/d); Excluded from Study or Analysis: missing anthropometric data at 22y | Exposure: Carbonated soft drinks including cola, cordials, or fruit drink concentrate, and fruit juice drinks with the exclusion of 100% juice. 1 svg=250 mL or 261g; Comparator: Categorical and continuous intake; Categorical: non-consumers, ≤1 svg/day, >1 svg/day; Continuous: 100g/day; Exposure Assessment Methods and Timing:; - Validated, semi-quantitative parent-assisted FFQ, estimates usual intake over past year. Participants reported frequency of consumption (never, rarely, # times/month, # times/week, # times/day) and usual portion size. Frequency was converted to daily equivalents and multiplied by usual portion size to derive daily consumption.; - Baseline (14y); Outcomes and Assessment Methods:; - Body weight, height, and WC measured by study staff; BMI calculated from height and weight. IOTF age- and sex-specific BMI cut-offs used to classify overweight/obesity at 14y. Overweight or obesity at 22y defined as BMI≥25 kg/m2.; - 14y, 22y | [underlined: WC at 22y], cm, β (95% CI), multivariable regression; SSB as continuous variable (100g/d); Not adjusted for TEI: 0.41 (0.04, 0.78), P=0.03; TEI-adjusted: 0.34 (−0.04, 0.71), P=0.08; SSB as categorical variable; Not adjusted for TEI: non-consumer: ref; ≤1 svg/d: 0.39 (−3.49, 4.27), P=0.84; >1 svg/d: 4.47 (0.35, 8.58), P=0.03; P-trend<0.0001; TEI-adjusted:; non-consumer: ref; ≤1 svg/d: 0.35 (−3.56, 4.26), P=0.86; >1 svg/d: 4.09 (−0.04, 8.22), P=0.05; P-trend<0.0001; [underlined: BMI at 22y], kg/m2, β (95% CI), multivariable regression; SSB as continuous variable (100g/d); 0.19 (0.04, 0.33), P=0.01; Adjusting for TEI did not change significance; SSB as categorical variable; non-consumer: ref; ≤1 svg/d: 0.32 (−1.27, 1.90), P=0.70; >1 svg/d: 2.00 (0.32, 3.67), P=0.02; P-trend<0.0001; Adjusting for TEI did not change significance; [underlined: Risk of Overweight or Obesity at 22y], OR (95% CI), multivariable regression; SSB as continuous variable (100g/d); 1.10 (1.02, 1.18), P=0.01; Adjusting for TEI did not change significance; SSB as categorical variable; non-consumer: ref; ≤1 svg/d: 0.96 (0.41, 2.25), P=0.92; >1 svg/d: 1.87 (0.76, 4.62), P=0.18; P-trend=0.002; Adjusting for TEI did not change significance | Model Adjustments:; - TEI: yes and no; - Key confounders: sex, age, socioeconomic position (maternal education, family income), anthropometry at baseline (baseline BMI, WC, overweight or obesity), physical activity, diet quality (healthy and western dietary pattern scores); - Other: Other beverage intake: water, tea/coffee, diet drink, 100% fruit juice, and milk; dietary misreporting; Limitations:; - Did not account for key confounders: race and/or ethnicity; - Exposure data only measured at baseline; High attrition/missing data; No preregistered data analysis plan; Funding:; University of Western Australia, Curtin University, Telethon Kids Institute, Women and Infants Research Foundation, Edith Cowan University, Murdoch University, University of Notre Dame Australia, Raine Medical Research Foundation, National Health Medical Research Council
Zulfiqar, 2019^110^; PCS, Longitudinal Study of Australian Children (LSAC), Australia; Analytic N=2,389; Included in meta-analysis: Yes; Participant characteristics at baseline:; Children; - Age: ~4.2y; - Female: 49%; - Race/ethnicity: 58% Australian; 30% Immigrants from high-income countries, 12% Immigrants from low/middle-income countries; - SEP: 24% High, 51% Middle, 24% Low; - Anthropometry: ~22% with overweight/obesity; - Physical activity: NR; - Diet quality: NR; - TEI: NR; - Study beverage intake at baseline: SSB intake: Highest intake shown in girls from low/middle-income countries from 4-9y of age; Excluded from Study or Analysis: age <4y or >11y; first-generation children, multiple births, mixed immigrant background of grandparents | Exposure: (no definition given, but could use definition in Wheaton, 2015 ‘SSBs: fruit juice; non-diet soft drink or cordial’; Comparator: SSB intake (categorical): None (ref); ≥ 1/d; Exposure Assessment Methods and Timing:; - Parent report during waves 1-3, child report on computer-based study instrument at wave 4; represents intake during previous 24hr; - At wave 1 (age 4-5y), and biennial waves 2-4 (age 6-8y, 8-9y,10-11y); Outcomes and Assessment Methods:; - Weight measured to nearest 50 g using Salter Australia bathroom scales; Height measured to nearest 0.1 cm using portable rigid stadiometer; Age- and sex-specific BMI calculated; Child overweight/obesity defined according to International Obesity Task Force age-and-sex-specific criteria (cut off points of 25 and 30 kg/m2 for overweight and obesity, respectively – extrapolated to children); - At wave 1 (age 4-5y), and biennial waves 2-4 (age 6-8y, 8-9y,10-11y) | [underlined: Overweight/Obesity at age 10-11y, per daily SSB intake], Logistic regression, OR (95% CI); Boys (n=2115); None (ref) versus; v≥ 1/d: 1.01 (0.80, 1.29); Immigrant Boys (n=883); None (ref) versus; v≥ 1/d: 1.01 (0.80, 1.28); Girls (n=2000); None (ref) versus; v≥ 1/d: 1.08 (0.87, 1.35); Immigrant Girls (n=843); None (ref) versus; v≥ 1/d: 1.08 (0.86, 1.35) | Model Adjustments:; - TEI: no; - Key confounders: sex, age, race/ethnicity, socioeconomic position (household income, parental education and employment); - Other: Breastfeeding, birth weight, siblings, sleep issues, foreign language spoken at home, maternal partnership status; Limitations:; - Did not account for key confounders: anthropometry at baseline, physical activity, diet quality,; - 46% attrition without information on non-completers, Unclear exposure definition, Exposure data collection tool not validated, Unclear if % missing data was equal across exposure groups, No preregistered data analysis plan; Funding:; none

a Abbreviations: Δ: change; Σ4SF: sum of four skinfolds ADA: American Dental Association; Adj: adjusted; AGA: appropriate for gestational age; ANOVA: analysis of variance; AR: adiposity reboundβ: beta coefficient; BF: breastfed/breastfeeding; BMI: body mass index; BMIZ: BMI z-score; cc: cubic centimeter; CDC: Centers for Disease Control and Prevention; CI: confidence interval; CIHR: Canadian Institutes of Health Research; cm: centimeter; d: day(s); DEXA/DXA: dual energy x-ray absorptiometry; EBF: exclusive breastfeeding; EER: estimated energy requirement; EI: energy intake; EPA: Environmental Protection Agency; FDA: Food and Drug Administration; FF: formula-fed; FFQ: food frequency questionnaire; fl oz: fluid ounces; g: grams; GDM: gestational diabetes mellitus; hr: hour(s); HDI: Human Development Index; HHS: Department of Health and Human Services; HS: high school; IOTF: International Obesity Task Force; IQR: interquartile range; kcal: kilocalories; kg: kilogram; KHANES: Korea National Health and Nutrition Examination Survey; kJ: kilojoules; L: liter(s); lb: pounds; LGA: large for gestational age; LNCSB: low- and no-calorie sweetened beverages; m: meter; MELAA: Middle Eastern, Latin American, and African; MET: metabolic equivalent of task; min: minutes; MJ: megajoules; mL: milliliter; mm: millimeter; mo: month(s); MZ: monozygotic; N/A: not applicable; NCI: National Cancer Institute; NHLBI: National Heart, Lung, and Blood Institute; NICHD: Eunice Kennedy Shriver National Institute of Child Health and Human Development; NIDDK: National Institute of Diabetes and Digestive and Kidney Diseases; NIEHS: National Institute of Environmental Health Sciences; NIH: National Institutes of Health; NIHR: National Institute for Health and Care Research; NR: not reported; NRCT: non-randomized controlled trial; NS: not significant; NZ: New Zealand; OGTT: oral glucose tolerance test; OR: odds ratio; Oz: ounce; PCS: prospective cohort study; RCS: retrospective cohort study; RCT: randomized controlled trial; Ref: reference; RR: relative risk; RRR: relative risk reduction; SAAT: subcutaneous abdominal adipose tissue; SD: standard deviation; SDS: standard deviation score; SE: standard error; SEP: socioeconomic position; SES: socioeconomic status; SGA: small for gestational age; SSB: sugar-sweetened beverages; SSSD: sugar-sweetened carbonated soft drinks; svg: serving; TAAT: total abdominal adipose tissue; TEI: total energy intake; tsp: teaspoon; UK: United Kingdom; Unadj: unadjusted; USDA: United States Department of Agriculture; VAT: visceral adipose tissue; WAZ: weight-for-age z-score; WC: waist circumference; WIC: Special Supplemental Nutrition Program for Women, Infants, and Children; WHO: World Health Organization; WHZ: weight-for-height z-score; wk: week(s); WLZ: weight-for-length z-score; y: year(s)

Table 13 Risk of bias for randomized controlled trials examining sugar-sweetened beverage consumption and growth, body composition, and risk of obesity in infants, children, and adolescents^a^

Article | Randomization | Randomization Identification of participants-randomization | Deviations from intended interventions (effect of assignment) or (per-protocol) | Missing outcome data | Outcome measurement | Selection of the reported result | Overall risk of bias
De Ruyter, 2012 ^15^ | LOW | NOT APPLICABLE | LOW | LOW | LOW | LOW | LOW
Ebbeling, 2006 ^23^ | SOME CONCERNS | NOT APPLICABLE | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Ebbeling, 2012 ^22^ | SOME CONCERNS | NOT APPLICABLE | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Katan, 2016 ^46^ | LOW | NOT APPLICABLE | LOW | LOW | LOW | LOW | LOW
Wang, 2022 ^95^ | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS

a Possible ratings of low, some concerns, or high determined using the “Cochrane Risk-of-bias 2.0” (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2019 version)” ( Sterne JAC, Savović J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ 2019; 366: l4898. doi:10.1136/bmj.l4898.31462531 )

Table 14 Risk of bias for observational studies examining sugar-sweetened beverage consumption and growth, body composition, and risk of obesity in infants, children, and adolescents^a^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Infants and Young Children (up to 24 months)
Amaro-Rivera, 2019 ^3^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Chaidez, 2014 ^12^ | SOME CONCERNS | LOW | LOW | LOW | HIGH | LOW | HIGH | HIGH
Garden, 2011 ^30^ | SOME CONCERNS | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Garden, 2012 ^31^ | SOME CONCERNS | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Goh, 2022 ^33^ | SOME CONCERNS | HIGH | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Hwang, 2020 ^41^ | HIGH | HIGH | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Leermakers, 2015a ^55^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Leermakers, 2015b ^54^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Lewis, 2020 ^56^ | HIGH | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Li, 2008 ^57^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | HIGH | SOME CONCERNS | SOME CONCERNS | HIGH
Mahoney, 2018 ^63^ | HIGH | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Pan, 2014 ^75^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | HIGH
Quah, 2019 ^78^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Sonneville, 2015 ^84^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Vandyousefi, 2021 ^91^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Wu, 2021 ^101^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Wu, 2022 ^100^ | SOME CONCERNS | HIGH | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Children and Adolescents
Altman, 2015 ^1^ | SOME CONCERNS | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Alviso-Orellana, 2018 ^2^ | HIGH | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Ambrosini, 2013 ^4^ | SOME CONCERNS | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Arenaza, 2020 ^5^ | HIGH | LOW | LOW | SOME CONCERNS | SOME CONCERNS | LOW | LOW | HIGH
Bennett, 2022 ^6^ | HIGH | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Berkey, 2004 ^7^ | HIGH | LOW | LOW | LOW | HIGH | LOW | HIGH | HIGH
Bigornia, 2015 ^8^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Blum, 2005 ^9^ | HIGH | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Cantoral, 2016 ^10^ | HIGH | LOW | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | HIGH
Carlson, 2012 ^11^ | HIGH | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS | HIGH
Chen, 2019 ^13^ | HIGH | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
DeBoer, 2013 ^16^ | HIGH | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
De Coen, 2014 ^14^ | LOW | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Dong, 2015 ^17^ | HIGH | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Drenowatz, 2013 ^18^ | HIGH | HIGH | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Dubois, 2007 ^19^ | HIGH | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Dubois, 2016 ^111^ | HIGH | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Dubuisson, 2012 ^20^ | HIGH | HIGH | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Durao, 2015 ^21^ | HIGH | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Enes, 2013 ^24^ | HIGH | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
English, 2022 ^25^ | SOME CONCERNS | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Faith, 2006 ^26^ | HIGH | LOW | SOME CONCERNS | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Field, 2014 ^27^ | HIGH | LOW | LOW | LOW | HIGH | SOME CONCERNS | SOME CONCERNS | HIGH
Fiorito, 2009 ^28^ | HIGH | LOW | LOW | LOW | LOW | LOW | HIGH | HIGH
French, 2012 ^29^ | HIGH | HIGH | SOME CONCERNS | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Goff, 2019 ^32^ | HIGH | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Gopinath, 2013 ^34^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | HIGH | HIGH
Guerrero, 2016 ^35^ | HIGH | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Haines, 2007 ^36^ | HIGH | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | HIGH
Hasnain, 2014 ^37^ | LOW | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
He, 2022 ^38^ | HIGH | SOME CONCERNS | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | HIGH
Hooley, 2012 ^39^ | HIGH | HIGH | LOW | HIGH | HIGH | LOW | SOME CONCERNS | VERY HIGH
Hur, 2016 ^40^ | HIGH | HIGH | LOW | LOW | HIGH | LOW | HIGH | HIGH
Hwang, 2020 ^41^ | HIGH | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Jensen, 2013a ^42^ | HIGH | HIGH | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Jensen, 2013b ^43^ | HIGH | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Johnson, 2007 ^45^ | SOME CONCERNS | LOW | SOME CONCERNS | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Johnson, 2012 ^44^ | HIGH | HIGH | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Kuhl, 2014 ^48^ | HIGH | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Kral, 2008 ^47^ | HIGH | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Kunaratnam, 2020 ^49^ | HIGH | SOME CONCERNS | SOME CONCERNS | LOW | VERY HIGH | LOW | SOME CONCERNS | VERY HIGH
Larson, 2018 ^50^ | HIGH | LOW | LOW | LOW | HIGH | SOME CONCERNS | SOME CONCERNS | HIGH
Laurson, 2008 ^52^ | HIGH | HIGH | LOW | LOW | LOW | LOW | SOME CONCERNS | HIGH
Laska, 2012 ^51^ | SOME CONCERNS | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Lee, 2015 ^53^ | SOME CONCERNS | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Lewis, 2020 ^56^ | HIGH | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Libuda, 2008 ^58^ | HIGH | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Lim, 2009 ^59^ | HIGH | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Lipsky, 2015 ^60^ | LOW | SOME CONCERNS | LOW | LOW | SOME CONCERNS | HIGH | SOME CONCERNS | HIGH
Ludwig, 2001 ^61^ | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Macintyre, 2018 ^62^ | SOME CONCERNS | HIGH | SOME CONCERNS | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Malihi, 2021 ^64^ | HIGH | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Marshall, 2018 ^65^ | HIGH | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Marshall, 2019 ^66^ | HIGH | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Millar, 2014 ^67^ | HIGH | HIGH | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Mirmiran, 2015 ^68^ | HIGH | HIGH | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Mrdjenovic, 2003 ^69^ | HIGH | SOME CONCERNS | HIGH | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Muckelbauer, 2016 ^70^ | HIGH | HIGH | LOW | LOW | LOW | LOW | SOME CONCERNS | HIGH
Mundt, 2006 ^71^ | HIGH | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Newby, 2004 ^72^ | SOME CONCERNS | LOW | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | HIGH
Nissinen, 2009 ^73^ | HIGH | SOME CONCERNS | HIGH | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Olsen, 2012 ^74^ | HIGH | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Pereyra-Gonzales, 2023 ^76^ | HIGH | HIGH | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Phillips, 2004 ^77^ | HIGH | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Quah, 2019 ^78^ | HIGH | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Quick, 2013 ^79^ | HIGH | SOME CONCERNS | LOW | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | HIGH
Seo, 2015 ^80^ | HIGH | HIGH | SOME CONCERNS | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Seum, 2022 ^81^ | HIGH | HIGH | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Shroff, 2014 ^82^ | HIGH | HIGH | SOME CONCERNS | SOME CONCERNS | HIGH | LOW | SOME CONCERNS | HIGH
Sichieri, 2013 ^83^ | HIGH | HIGH | SOME CONCERNS | SOME CONCERNS | HIGH | LOW | SOME CONCERNS | HIGH
Stoof, 2013 ^85^ | HIGH | SOME CONCERNS | LOW | SOME CONCERNS | HIGH | LOW | SOME CONCERNS | HIGH
Striegel-Moore, 2006 ^86^ | HIGH | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS | HIGH
Tam, 2006 ^87^ | HIGH | SOME CONCERNS | SOME CONCERNS | LOW | HIGH | LOW | LOW | HIGH
Thurber, 2017 ^88^ | SOME CONCERNS | HIGH | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Traub, 2018 ^89^ | HIGH | HIGH | SOME CONCERNS | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Trier, 2016 ^90^ | HIGH | HIGH | LOW | SOME CONCERNS | LOW | LOW | SOME CONCERNS | HIGH
Vanselow, 2009 ^92^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Viner, 2006 ^93^ | HIGH | SOME CONCERNS | LOW | SOME CONCERNS | HIGH | HIGH | SOME CONCERNS | HIGH
Vinke, 2020 ^94^ | HIGH | SOME CONCERNS | SOME CONCERNS | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Wang, 2022 ^95^ | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | HIGH
Welsh, 2005 ^96^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Wheaton, 2015 ^97^ | SOME CONCERNS | HIGH | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Whetstone, 2012 ^98^ | HIGH | SOME CONCERNS | VERY HIGH | LOW | HIGH | LOW | HIGH | VERY HIGH
Wijga, 2010 ^99^ | HIGH | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Yiotaldiotariotam, 2013 ^102^ | HIGH | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Yoon, 2022 ^103^ | SOME CONCERNS | LOW | SOME CONCERNS | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Zhang, 2020 ^104^ | HIGH | HIGH | SOME CONCERNS | LOW | SOME CONCERNS | LOW | HIGH | HIGH
Zheng, 2014 ^109^ | HIGH | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Zheng, 2015a ^105^ | HIGH | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Zheng, 2015b ^106^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Zheng, 2015c ^108^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Zheng, 2019 ^107^ | SOME CONCERNS | LOW | LOW | LOW | VERY HIGH | LOW | SOME CONCERNS | HIGH
Zulfiqar, 2019 ^110^ | HIGH | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH

a Possible ratings of low, some concerns, high, very high, no information, or not applicable were determined using the “Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)” tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602. *Low risk of bias except for concerns about uncontrolled confounding.

Table 15 Evidence examining the relationship between sugar-sweetened beverage consumption and body composition and risk of obesity in adults^a^

Study and Participant Characteristics | Intervention, Comparator, & Outcomes | Results | Methodological considerations
Randomized controlled trials
Campos, 2015^122^; RCT-Parallel, Switzerland; Baseline N=31, Analytic N=27 (Attrition: 13%);; Power: NR; Included in meta-analysis: yes; Study purpose: To evaluate whether an intervention in which SSBs were replaced by LNCSB would reduce markers of NAFLD in highSSB consumers with overweight or obesity.; Participant characteristics at baseline: Adults with overweight/obesity; - Age: Range: 18-40y; - Female: 48%; - Race/ethnicity: NR; - SEP: NR; - Anthropometry: BMI Mean (SD), ~31.0 (1.8) kg/m^2^; Obesity: 52%; - Physical activity: ~9,000 steps/d (sig higher in SSB group at baseline); - Smoking: NR; - Alcohol intake: NR; - Diet quality: NR; - TEI: ~2,300 kcal/d; - Study beverage intake at baseline: Sugars from SSB, Mean g/d:; SSB group: Baseline: 94.6, 6wk: 0, 12wk: 0; LNCSB group: Baseline: 93.8, 6wk: 80.5, 12wk: 86.8; Include: BMI >25kg/m2, ≥2, 22oz SSB/d; (carbonated soft drinks and sugar-sweetened tea) | Intervention: Habitual SSB consumers (≥2, 22oz svg/d) of carbonated soft drinks or sugar-sweetened tea maintained intake for 12wk (beverages provided by study); Comparator: Habitual SSB consumers replaced their normal SSB intake with LNCSB (≥2, 22oz svg/d) for 12wk; (beverages provided by study); Duration: 12wk; Compliance: >90% based on returned packages in both groups; Intake changed as expected (see ‘Study Beverage Intake’ column); Outcomes and assessment methods:; - Weight and body composition (bioimpedancemetry) monitored every other week; Methods NR; - Body composition, methods NR; - Visceral adipose tissue (VAT) measured with MRS; - Baseline, wk6, wk12 | [underlined: Fat mass %], Mean (SEM); Within group: Wk4, Wk16; SSB: 34.1 (2.4), 34.8 (2.3); ASB: 35.3 (1.8), 34.0 (2.1); Change from baseline, between groups:; P=NS; [underlined: Fat-free mass %], Mean (SEM); Within group: Wk4, Wk16; SSB: 64.1 (2.7), 65.1 (2.3); ASB: 64.6 (1.8), 65.9 (2.1); Change from baseline, between groups:; P=NS; [underlined: VAT], cm3, Mean (SEM); Within group: Wk4, Wk16; SSB: 759.2 (165.5), 747.4 (156.7); ASB: 684.2 (130.5), 582.4 (90.3); Change from baseline, between groups:; P=NS; [underlined: Weight], kg, Mean (SEM); Within group: Wk4, Wk16; SSB: 90.1 (4.0), 91.0 (3.9); ASB: 95.1 (3.8), 93.7 (3.7); Change from baseline, between groups:; P=NS; [underlined: BMI, kg/m]^2^, Mean (SEM); Within group: Wk4, Wk16; SSB: 30.6 (1.5), 31.0 (1.4); ASB: 31.5 (1.2), 31.0 (1.2); Change from baseline, between groups:; P=NS | Model adjustments:; - TEI: no; Limitations:; - Randomization and allocation methods NR, no power calculation, differential attrition: all non-completers from LNCSB group, body comp methods NR, trial registry did not include data analysis plan; Funding:; Swiss National Foundation for Science; Fondation Raymond Berger pour la recherche sur le diabete et les maladies metaboliques
Ebbeling, 2020^131^; RCT-Parallel, U.S.; Baseline N=203, Analytic N=186 (Attrition: 8%);; Power: Sample size sample size of 270; participants to detect, with 80% power; Included in meta-analysis: yes; Study purpose: To compare effects of consuming SSB, Artificially-sweetened beverage (ASB), or Unsweetened beverage (USB) on cardiometabolic risk factors, body weight and adiposity, and sweet taste preference in habitual SSB consumers.; Participant characteristics at baseline: Adults; - Age: Mean ~27y; - Female: 73%; - Race/ethnicity: 51% White; 20% Black; 13% Asian; 16% Multiple/ Unknown/ Other; - SEP: Education: Some high school: 2% High school or GED: 25% Some college/ vocational: 27%, Associate’s/Bachelor’s: 37%, Graduate school: 26%; Household income: <30K: 28%, 30K-59,999: 25%, 60K-89,999: 13%, >90K: 17%; - Anthropometry: Mean (SD): Weight (kg): ~76.6 (16.1); BMI (kg/m^2^) ~26.2 (4.8); - Physical activity: Mean MET ~1.59; - Smoking: NR; - Alcohol intake: NR; - Diet quality: NR; - TEI: ~2,130 kcal/d; - Study beverage intake at baseline: Baseline SSB intake, Mean (SD), svg/d; SSB: 1.4 (1.1), ASB: 1.4 (1.4), USB: 1.8 (1.3) 12mo SSB intake, svg/d; SSB: 2.5 (1.8), ASB: 0.1 (0.3), USB: 0.2 (0.5); Inclusion: adults 18-40y, consume at least 1 serv/d (12 fl oz) of SSB, BMI from 18.5 to 40.; Exclusion: fasting blood glucose >100 mg/dL, major medical or psychiatric illness, chronic use of any medication that could affect study outcomes, heavy smoker (>10 cigarettes/d), pregnancy in preceding 12 months or plans to become pregnant, lactation preceding 3 months, and change in hormonal contraceptives in preceding 3 months | Intervention: Participants were randomly assigned to 1 of 3 groups: SSB, ASB, USB (water, flavored or unflavored). Within their intervention beverage type, participants selected their desired beverages that were delivered to their homes with a frequency/amount meant to match baseline SSB consumption. Study messaging and bi-weekly phone calls reinforced which beverages to consume and which to avoid. Randomization was stratified by sex, ethnicity/race, and baseline BMI; Comparator: Artifical sweetened beverage (ASB) and unsweetened beverage (USB) groups; Intake changed as expected (see ‘Study Beverage Intake’ column); Outcomes and assessment methods: Body weight and height were measured using an electronic scale and a wallmounted stadiometer. Whole-body fat mass and trunk fat mass were assessed by DXA; Baseline and 12 month follow up | [underlined: Change in fat mass, kg]: p-value; SSB: 1.0 (0.5); ASB: 0.1 (0.5); USB: 0.1 (0.4); Change between groups 0.27; [underlined: Change in whole body fat mass by][underlined: tertile of baseline trunk fat, kg]; Tertile 1: SSB: 0.9 (0.8), ASB: 1.0 (0.7), USB: 0.0 (0.9), p = 0.64; Tertile 2: SSB: −0.4 (0.7), ASB: −0.6 (0.8), USB: 1.2 (0.6), p = 0.12; Tertile 3: SSB: 2.8 (0.8), ASB: −0.1 (0.8), USB: −1.1 (0.8), p = 0.002; Overall effect modification: p=0.004; [underlined: Change in weight, kg]: Mean (SE) p-value; SSB: 1.2 (0.6), p=0.03; ASB: 0.6 (0.6), p=0.32; USB: 0.7 (0.5), p=0.22; Change between groups p=0.66; [underlined: Change in body weight by tertile of][underlined: baseline trunk fat, kg]:; Tertile 1: SSB: 0.2 (1.0), ASB: 1.1 (0.9), USB: −0.0 (1.1), p = 0.70; Tertile 2: SSB: 0.2 (0.9), ASB: −0.2 (1.0), USB: 1.9 (0.8), p = 0.22; Tertile 3: SSB: 4.4 (1.0), ASB: 0.5 (0.9), USB: −0.2 (0.9), p = 0.002; Overall effect modification: p=0.006 | Model adjustments:; - TEI: no; Limitations:; - Methods for randomization and concealment NR; No preregistered data analysis plan; Funding:; NHLBI; NIDDK; National Center for Research Resources; Harvard Catalyst Clinical and Translational Science Center; New Balance Foundation
Hernández-Cordero, 2014^142^; RCT-Parallel, Mexico; Baseline N=240, Analytic N=240 (Attrition: 21%);; Power: Powered to observe a 31(58) mg/dL decrease in plasma TG concentrations and a weight loss of 1.8(3.4) kg with a sample size of 120 cases, 2-sided tests, with 90% power and α of 0.05, and >75% attrition; Included in meta-analysis: yes; Study purpose: Study purpose: to determine if replacing SSBs with water affects plasma triglycerides (primary outcome), weight, and other cardiometabolic factors; Participant characteristics at baseline: Adult women with overweight or obesity; - Age: 33 (6.7)y; - Female: 100%; - Race/ethnicity: 100% Hispanic; - SEP: Socioeconomic level index, composite score including age, years of education, and housing condition: WEP: 0.11(1.34), EP: −0.14(1.33), p>0.05; - Anthropometry: Overweight: 46%; Obesity: 54%; - Physical activity: METs/d: 1.455(0.004); - Smoking: 31% current; - Alcohol intake: NR; - Diet quality: NR; - TEI: ~2,035kcal/d; - Study beverage intake at baseline: SSB: ~1,111mL/d, ~408kcal/d, ~21% of TEI; Include: age 18-45y, BMI 25-<39kg/m2, SSB intake ≥250kcal/d; Exclude: >5% weight loss in past 6mo, current weight-reducing diet, pregnancy in past 6mo, current, or planned, medical condition that affects metabolic function, hx of MI or heart surgery, medication affecting metabolism, recent psychiatric hospitalization, muscle-increasing regime or anabolic use, excessive alcohol (≥21 drinks/wk) | Intervention: Participants with habitually high SSB intake (≥250 cal/d) were randomized to 1 of 2 groups; water+education (WEP) or education only (EP).; EP: habitual SSB intake ≥250 cal/d plus monthly face-to-face nutrition counseling with a dietitian and a psychologist where they identified a healthy diet goal for the next month. The WEP and EP groups met separately and received equal attention.; Comparator: The WEP group received bottled water (2-3 L/d) with monthly faceto-face nutrition counseling with a dietitian and a psychologist, including individualized and group meetings targeted to the rationale and strategies to increase water intake, reduce SSB intake, and substitute water for SSBs.; Duration: 9mo; Compliance: Attendance (Mean (SD): WEP: 7.3(2.4) sessions, EP: (6.4(2.4) sessions, p = 0.01; Outcomes and assessment methods:; - Weight measured in tight-fitting swimsuits or spandex shorts without shoes with a Tanita digital scale.; - Height measured by using a calibrated, wall-mounted stadiometer; - Waist circumference measured following standard procedures; - Total body fat evaluated by using air displacement plethysmography; - Weight, BMI, WC (Baseline, 3mo, 6mo, 9mo); - Body fat % (Baseline, 9mo); - Height (Baseline) | [underlined: Body fat percent], repeated measures mixed effects model, Mean(SE) baseline, 9mo, p-interaction; WEP: 42.5(0.1), 41.6(0.1); EP: 42.2(0.1), 41.5(0.2), between group p=0.90; [underlined: Change in body fat percent from][underlined: baseline],; WEP: −0.8(0.4); EP: −0.8(0.6), between group p=0.90; [underlined: Waist circumference (cm)], repeated measures mixed effects model, Mean(SE) baseline, 3mo, 6mo 9mo, p-interaction; WEP: 98.3(0.3), 97.8(0.3), 96.9(0.2), 97.3(0.3); EP: 98.5(0.3), 97.9(0.3), 97.9(0.3), 97.3(0.3), between group p=0.80; [underlined: Change in waist circumference from baseline]; WEP: −1.0(0.3), −1.4(0.3), −1.0(0.4); EP: −0.5(0.3), −0.6(0.5), −1.3(0.7), between group p>0.05 at all time points; [underlined: Weight (kg)]; WEP: 76.9(0.3), 76.4(0.3), 75.6(0.3), 75.7(0.3); EP: 76.0(0.3), 75.6(0.3), 75.3(0.3), 75.3(0.3), between group p=0.40; [underlined: Change in weight from baseline],; WEP: −1.0(0.2), −1.4(0.3), −1.2(0.4); EP: −0.5(0.2), −0.7(0.3), −0.8(0.4), between group p=0.40; [underlined: BMI (kg/m]^2^),; WEP: 31.0(0.1), 30.6(0.1), 30.5(0.1), 30.5(0.1); EP: 31.0(0.1), 30.8(0.1), 30.7(0.1), 30.7(0.1), between group p=0.40; [underlined: Change in BMI from baseline]; WEP: −0.40(0.08), −0.54(0.11), −0.50(0.14); EP: −0.20(0.08), −0.30(0.14), −0.33(0.15), between group p=0.40 | Model adjustments:; - TEI: no; Limitations:; - Control group (EP) was not required to maintain SSB intake; Funding:; Danone Research Center
Higgins, 2019^143^; RCT-Parallel, U.S.; Baseline N=154, Analytic N=123 (Attrition: 20%); Power: Power: >25 individuals per treatment group and ~4% variance (SD=1.78 kg body weight), α<0.05, 80% power to detect differences in average weight gain of 2.8 kg; Included in meta-analysis: yes; Study purpose: To compare the effects of 4 common low-calorie sweeteners and sucrose on body weight, body composition, energy intake, energy expenditure, appetite, and glycemia in adults with overweight or obesity; Participant characteristics at baseline: Adults with overweight/obesity; - Age: 28y; - Female: 56%; - Race/ethnicity: NR; - SEP: NR; - Anthropometry: ~29kg/m2; - Physical activity: Sport index ~2.5; - Smoking: NR; - Alcohol intake: NR; - Diet quality: NR; - TEI: ~2,300 kca/d; - Study beverage intake at baseline: Habitual consumption of low-calorie sweeteners: ≤1 time/wk; SSB consumption: NR; Include: 18–60 y of age, BMI 25-40 kg/m2, healthy (i.e., no history of diabetes, hypertension, etc.), low consumers of LNCSB (≤1 time/wk), weight stable (weight change ≤3kg in past 3mo), TFEQ restraint score <14 | Intervention: Participants randomized to 1 of 5 beverage sweetener treatments: sucrose, saccharin, aspartame, RebA, or sucralose; they consumed 1.25-1.75L/d (Kool-Aid) depending on body weight. No other dietary recommendations were given.; SSB group: Sucrose-sweetened beverage (fruit-flavored Kool-Aid; 1.25-1.75 L/d depending on baseline body weight), n=39; Comparator: Low-calorie sweetener (LCS) beverage (fruit-flavored Kool-Aid; 1.25-1.75 L/d depending on baseline body weight); - Saccharin-sweetened, n=29; - Aspartame-sweetened, n=30; - RebA-sweetened, n=28; - Sucralose-sweetened, n=28; Duration: 12wk; Compliance: Urinary biomarker para-aminobenzoic; acid (PABA) incorporated into test; beverage powders - results did not vary between groups; Outcomes and assessment methods:; - Weight and total body water measured using Tanita Body Composition Analyzer; - Height measured with Holtain stadiometer at baseline; - Body composition (total fat mass, total fat-free mass, total tissue percentage fat, android fat mass, and gynoid fat mass) measured using DXA at baseline and at week 12; Baseline and every 2wk until 12wk | [underlined: Total Fat Mass change, kg], Mean (SE); [underlined: Change within group]: From 0wk-12wk; Sucrose (n=39): 1.35 (0.25), P<0.001; Saccharin (n=29): 0.48 (0.23), P=NS; Aspartame (n=30): 0.49 (0.23), P=NS; RebA (n=28): 0.09 (0.23), P=NS; Sucralose (n=28): −0.31 (0.24), P=NS; [underlined: Change over 12wk], compared to Sucrose:; Sucrose>Saccharin, Aspartame, RebA; Sucralose, P<0.05; [underlined: Total Fat-Free Mass change, kg], Mean (SE); [underlined: Change within group]: From 0wk-12wk; Sucrose (n=39): 0.84 (0.20), P=0.001; Saccharin (n=29): 0.70 (0.18), P=0.006; Aspartame (n=30): 0.63 (0.18), P=0.01; RebA (n=28): 0.25 (0.18), P=NS; Sucralose (n=28): −0.33 (0.19), P=NS; [underlined: Change over 12wk], compared to Sucrose:; Sucrose vs. Saccharin, Aspartame, P>0.05; Sucrose>RebA, Sucralose, P<0.05; [underlined: Weight change, kg], Mean (SE); [underlined: Change within group]: From 0wk-12wk; Sucrose (n=39): 1.85 (0.36), P<0.001; Saccharin (n=29): 1.18 (0.36), P=0.02; Aspartame (n=30): 0.73 (0.35), P≥0.07; RebA (n=28): 0.60 (0.36), P≥0.07; Sucralose (n=28): −0.78 (0.36), P≥0.07; [underlined: Change over 12wk], compared to Sucrose:; Sucrose versus. Saccharin: P=0.21; Sucrose>Aspartame (P≤0.02), RebA; (P≤0.02), Sucralose (P<0.001); [underlined: BMI change, kg/m]^2^, Mean (SE); [underlined: Change within group]: From 0wk-12wk; Sucrose (n=39): 0.62 (0.12), P<0.04; Saccharin (n=29): 0.41 (0.12), P<0.04; Aspartame (n=30): 0.22 (0.12), P>0.07; RebA (n=28): 0.20 (0.12), P<0.07; Sucralose (n=28): −0.27 (0.12), P≥0.07; [underlined: Change over 12wk], compared to Sucrose:; Sucrose versus. Saccharin: P=NS; Sucrose>Aspartame (P<0.05), RebA; (P<0.05), Sucralose (P<0.05) | Model adjustments:; - TEI: no; Limitations:; - No information on allocation concealment, no information on non-completers, trial registry did not contain data analysis plan; Funding:; USDA
Kendig, 2023^149^; RCT-Parallel, Australia; Baseline N=118, Analytic N=80 (Attrition: 32%);; Power: To detect the effects of our diet intervention with 80% power, a more conservative effect size of d = 0.70, and with a = 0.05 (two-tailed), a sample size of 34 per group was required.; Included in meta-analysis: no; Study purpose: To examine changes in cognitive, metabolic, and affective parameters in young adult SSB consumers who replaced normal SSB intake with non-nutritive ‘diet’ drinks or water, or maintain usual SSB intake (control); Participant characteristics at baseline: Young adults; - Age: 23 (3.9)y; - Female: 40%; - Race/ethnicity: NR; - SEP: NR; - Anthropometry: BMI 23.2 (3.6) kg/m^2^; - Physical activity: NR; - Smoking: NR; - Alcohol intake: NR; - Diet quality: NR; - TEI: NR; - Study beverage intake at baseline: All drank >2 L/wk of SSB; Exclusion criteria: age <18 or >35y; BMI <17.5 or >30 kg/m2; regularly consumed <2 L/wk of SSB; participants with average weekly SSB intake >1.5 times their group’s IQR during intervention | Intervention: Participants received 4.5L/week of their group’s beverage type, selecting from a range of commercially available carbonated beverages (SSB & diet drink groups) or bottled water (water group); asked to abstain from sweetened drinks beyond those provided and not consume >3cans/d; no further dietary restrictions; Comparator: Water (4.5 L/wk as 12 x 375mL cans); n=25; Artificially-sweetened beverages (4.5 L/wk as 12 x 375mL cans and ≤3 cans/d); n=28; Duration: 12wk; Compliance: Questionnaire on weekly drink adherence and weekly SSB intake; Outcomes and assessment methods:; - Weight, height, and waist circumference were measured by study staff and waist circumference to height ratio was calculated. Body fat and skeletal muscle were measured using bio-electrical impedance.; - At baseline, 6wk, 12wk, and 24wk (12wk follow-up) | [underlined: Change in waist circumference to height][underlined: ratio], Mean (SE); [underlined: Over 12wk intervention]; Water versus Artificially-sweetened beverages versus SSB: data NR (figure only), P=0.803; [underlined: After 12wk follow-up] (n=67); Water versus Artificially-sweetened beverages versus SSB: data NR (figure only), P=0.291; [underlined: Change in body fat percentage], Mean (SE); [underlined: Over 12wk intervention]; Water versus Artificially-sweetened beverages versus SSB: data NR (figure only), P=0.457; [underlined: After 12wk follow-up] (n=67); Water versus Artificially-sweetened beverages versus SSB: data NR (figure only), P=0.027; Diet > Water: 2.72 (0.71, 4.73), p=0.009; Diet = SSB, p=NS; [underlined: Change in skeletal muscle percentage], Mean (SE); [underlined: Over 12wk intervention]; Water versus Artificially-sweetened beverages versus SSB: data NR (figure only), P=0.35; [underlined: After 12wk follow-up] (n=67); Water versus Artificially-sweetened beverages versus SSB: data NR (figure only), P=0.015; Diet < Water: −1.56 (−2.56, −0.56); Diet = SSB, p=NS | Model adjustments:; - TEI: no; Limitations:; - Methods for randomization and concealment NR; Not sufficiently powered; Trial registry did not include data analysis plan; Funding:; Australian Research Council Discovery Project
Maersk, 2012^154^; RCT-Parallel, Denmark; Baseline N=60, Analytic N=47 (Attrition: 22%);; Power: NR; Included in meta-analysis: yes; Study purpose: To test the hypothesis that sucrose-sweetened cola (Coca Cola) increases ectopic fat including VAT4, total body fat accumulation, and metabolic risk factors compared with 3 alternative beverages: isocaloric semiskim milk, aspartame-sweetened cola (Coca Cola), and still mineral water.; Participant characteristics at baseline: adults with overweight and obesity; - Age: ~39y (Range 20-50y); - Female: 64%; - Race/ethnicity: NR; - SEP: NR; - Anthropometry: Mean BMI ~32 kg/m^2^ (Range 2640); - Physical activity: NR; - Smoking: NR; - Alcohol intake: NR; - Diet quality: NR; - TEI: NR; - Study beverage intake at baseline: Mean SSSD at baseline: 184 mL/d; Included healthy, nondiabetic participants with a BMI between 26-40 kg/m2, age 20-50y, and blood pressure <160/100 mm Hg. | Intervention: Participants consumed 1L/d of the test drink and were allowed to drink water, tea, coffee, and usual amount of alcohol; Sucrose-sweetened soft drink (SSSD;; Coca Cola; 1 L/d), n=10; Comparator: Still mineral water (Aqua d’or; 1 L/d), n=13; OR; Aspartame-sweetened cola (Coca Cola); Duration: 6mo; Compliance: Empty bottles or cartons every 3-4wk; 7-d dietary records at baseline, 3mo, 6mo; compliance NR; Outcomes and assessment methods:; Weight: method NR; Total fat mass and lean body mass determined by DXA; At baseline, 6mo follow-up | [underlined: Total fat mass, percent change over][underlined: 6mo, kg], ANOVA, Mean (SEM); Between groups:; Diet Cola: −0.52 (2.5); Water: 0.490 (2.6); SSSD: 3.14 (2.7), p = 0.8; [underlined: Lean mass, percent change over 6mo, kg], ANOVA, Mean (SEM) Between groups:; Diet Cola: 0.951 (0.8); Water: −0.189 (0.8); SSSD: 0.423 (0.8), p = 0.5; Data are also provided on subcutaneous abdominal adipose tissue (SAAT), visceral adipose tissue (VAT), and the ratio of the two; none were significant for the exposures of interest.; [underlined: Weight, percent change over 6mo kg], ANOVA, Mean (SEM); Between groups:; Diet cola: 0.114 (1.1); Water: 0.576 (1.0); SSSD: 1.28 (1.1), p = 0.8 | Model adjustments:; - TEI: yes (between-group differences NS at baseline or during study); Limitations:; - Baseline differences in VAT, skeletal muscle fat, and liver fat between groups; Methods for randomization and concealment NR; No power calculation; No preregistered data analysis plan; Funding:; Danish Council for Strategic Research; The Food Study Group/Danish Ministry of Food, Agriculture and Fisheries; Novo Nordic Foundation; Clinical Institute at Aarhus University, Denmark; Danish Dairy Company, Arla Foods
Tate, 2012^170^; RCT-Parallel, Choose Healthy Options Consciously; Everyday (CHOICE), U.S.; Baseline N=318, Analytic N=272 (Attrition: 15%);; Power: With 100 participants per arm and a set at 0.05, we had 90% power to detect a difference of 1.8 kg with an SD of 3.4 kg and 25% attrition; Included in meta-analysis: yes; Study purpose: To compare the replacement of caloric beverages with water or diet beverages (DBs) as a method of weight loss over 6 mo in adults and attention controls; Participant characteristics at baseline: Adults with overweight or obesity; - Age: Mean (SD): 42 (10.7)y (Range 18-65y); - Female: 84%; - Race/ethnicity: 40% white ; 54% Black; 6% other; - SEP: ~55% College graduate or beyond; - Anthropometry: BMI ~36.3kg/m^2^ (Range 25-49.9); - Physical activity: NR; - Smoking: 9% current smoker; - Alcohol intake: NR; - Diet quality: NR; - TEI: NR; - Study beverage intake at baseline: ~100-200 g/d; Included: BMI 25–49.9kg/m^2^; age 18-65y, consuming ≥280 kcal/d of caloric beverages (including SSBs, juice, juice drinks, sweetened coffee and tea, sweetened milk, sports drinks, and alcohol, excluding white milk); willing to make a dietary substitution recommended by the study; Excluded: recent weight loss of >5%, participation in other weight-loss or physical-activity research; lactation; recent or planned pregnancy, thyroid medication use, diabetes mellitus treated with oral medication or insulin; cancer in prior 5 y; history of MI or heart surgery; current psychiatric treatment; psychiatric hospitalization in past year; alcohol dependence; plans to move or unable to attend monthly group meetings; inadequate means to transport beverages; self-report of heart problems, frequent chest pains, or faintness or dizziness | Intervention: Participants with high habitual SSB intake (≥280kcal/d) assigned to 1 of 3 groups: attention control (maintain SSB intake), water, or diet beverages.; “Attention Control” (AC, n=105): equal treatment contact time and attention, monthly group sessions and weigh-ins, weekly monitoring, general weight-loss information, no weight-loss caloriereduction or physical activity goals, not encouraged to change beverage intake and were not provided with beverages.; Comparator: Diet beverages, n=105: replace ≥2 servings (≥200 kcal) per day of caloric with diet beverages of their choice; four 355–500-mL (12–16 oz) singleserving beverages per person per day were provided; 2nd Intervention Group: (Water, n=108): encouraged to replace ≥2 servings (≥200 kcal) per day of caloric beverages with water; four 355–500-mL (12–16 oz) single-serving beverages per person per day were provided; Duration: 6mo; Compliance:; Intakes of the noncaloric beverage substitutions (ie, water and DBs) were in the expected direction based on intervention assignment. Intake reduction of ~2 svg/d across both groups. AC group also reduced their caloric beverage consumption by 1 svg/d; Outcomes and assessment methods:; - Weight measured after 12h fast using digital scale; Height measured using stadiometer at baseline. Waist circumference measured at the iliac crest; - Baseline, 3mo, 6mo | [underlined: Waist circumference, cm], within group, over time: baseline, 3mo, 6mo, mean (95% CI), ITT; Control: 116.5 (113.9, 119.2), 116.8 (114.1, 119.5), 115.9 (113.2, 118.7), P=0.0107; Water: 115.1 (112.6, 117.6), 114.4 (111.9, 116.9), 113.1 (110.5, 115.8), P=0.0103; Diet beversus: 115.5 (112.5, 118.5), 114.9 (112.0, 117.8), 113.4 (110.5, 116.4), P=0.0103; Group x time interaction: control (ref); Diet beversus: P=0.21; Water: P=0.22; [underlined: Weight, kg], within group, over time: baseline, 3mo, 6mo, mean (95% CI), ITT; Control: 102.6 (99.1, 106.1), 101.1 (97.7, 104.6), 100.7 (97.2, 104.2), P<0.0001; Water: 98.4 (95.2, 101.6), 97.2 (94.0, 100.4), 96.5 (93.3, 99.7), P<0.0001; Diet beversus: 100.9 (97.1, 104.7), 99.0 (95.3, 102.7), 98.3 (94.5, 102.1), P<.0001; Group x time interaction: control (ref); Diet beversus: P=0.24; Water: P=0.99; Likelihood of achieving 5% weight loss, OR (95% CI), ITT; Control: (ref); Diet beversus: 2.29 (1.05, 5.01), P=0.004; Water: 1.87 (0.84, 4.14), P=0.13 | Model adjustments:; - TEI: no; Limitations:>; - Amount of carbonated and/or caffeinated versions of beverages was not taken into account; Trial registry did not include data analysis plan; Funding:; Nestle´ Waters USA
Vazquez-Duran, 2016^173^; RCT-Parallel, Mexico; Baseline N=148, Analytic N=146 (Attrition: 1%);; Power: Sample size of 31, which was increased by 20% loss to follow up, gave a total of 37 patients in each group. α=0.05, β=80% to detect −1.6% change in BMI in intervention group with SD 0.8; Included in meta-analysis: yes; Study purpose: To evaluate the effect of reducing consumption of beverages with caloric and noncaloric sweeteners on weight, body composition and blood pressure in young Mexican nursing students; all had habitual SSB intake (≥12 oz/d); Participant characteristics at baseline: Adult nursing students; - Age: Mean (SD): 22 (0.25) y; - Female: 81%; - Race/ethnicity: NR; - SEP: NR; - Anthropometry: BMI, mean (SD): 26.24 (0.36) kg/m2; Overweight: 45%; Obesity: 16%; - Physical activity: <1hr/d of vigorous physical; activity (inclusion criteria); - Smoking: NR; - Alcohol intake: NR; - Diet quality: NR; - TEI: NR; - Study beverage intake at baseline: NR; Included: nursing students, male and female gender, more than 18 years of age and consumed at least 12 ounces of sweetened beverages/d (based on values from the Mexican Ministry of Health).; Excluded: on a special diet, arterial hypertension, diagnosed with or without use of antihypertensive medications, hyperthyroidism or hypothyroidism, weight loss medications, diabetes mellitus, cardiovascular or psychiatric diseases, hormonal therapy, vigorous physical activity for more than one hour/d | Intervention: Participants assigned to 1 of 3 groups: 1) No sweetened beversus (USB): only plain water, lemon and hibiscus flavored water, coffee and tea without sugar were permitted; 2) only beverages with non-caloric sweeteners (ASB), plain water, lemon and hibiscus flavored water, coffee and tea without sugar were permitted; 3) no modification in consumption of beverages, and only given general recommendations about beverages; Comparator: Group 1: No sweetened beverages permitted (only plain water, lemon and hibiscus flavored water, coffee and tea without sugar), n=49; OR; Group 2: Only beverages with non-caloric sweeteners allowed (including plain water, lemon and hibiscus flavored water, coffee and tea without sugar), n=50; Duration: 6mo; Compliance: 24hr food record 1x/week for full 6-month intervention; ~80% of ppts in groups 1 & 2 stopped drinking soft drinks and industrialized juice; Outcomes and assessment methods: Weight and height measured according to anthropometric standardization reference manual; Body composition (resistance/height and phase angle) evaluated by bioelectric impedance analysis; Waist, hip, and arm circumferences evaluated according to the anthropometric reference manual; Baseline, 3mo and 6mo follow-up | All Linear regression, Mean (SD), per protocol; Waist Circumference % of change; Change over time, within group: 3mo, 6mo; SSB (Control): 0.53 (0.16), 0.62 (0.60); ASB: −1.56 (0.46), −1.23 (0.58); USB: −2.45 (0.44), −4.07 (0.54); Change over time, between groups: 6mo; SSB versus. USB, P<0.001; SSB versus.; ASB, P=NS; [underlined: Hip circumference % of change]; Change over time, within group: 3mo, 6mo; SSB (Control): 0.33 (0.27), 0.51 (0.31); ASB: −0.71 (0.35), −0.35 (0.46); USB: −1.63 (0.30), −3.00 (0.44); Change over time, between groups: 6mo; SSB versus. USB, P<0.001; SSB versus.; ASB, P=NS; [underlined: Resistance/height % of change]; Change over time, within group: 3mo, 6mo; SSB (Control): −0.43 (1.83), 0.34 (0.62); ASB: −0.85 (1.49), 2.00 (1.38); USB: −1.92 (1.61), −2.12 (0.95); Change over time, between groups: 6mo; SSB versus. USB, P=0.02; SSB versus.; ASB, P=NS; Phase angle % of change; Change over time, within group: 3mo, 6mo; SSB (Control): 3.02 (0.70), 3.58 (0.96); ASB: 5.57 (1.20), 4.92 (1.28); USB: 4.88 (0.76), 8.40 (0.85); Change over time, between groups: 6mo; SSB versus. USB, P<0.005; SSB versus.; ASB, P=NS; [underlined: BMI % of change], Linear regression, Mean (SD), per protocol; Change over time, within group: 3mo, 6mo; SSB (Control): 0.54 (0.06), 0.57 (0.07); ASB: −0.61 (0.08), 0.11 (0.06); No SSB: −1.75 (0.6), −3.34 (0.75); Change over time, between groups: 6mo; SSB versus. USB, P<0.001; SSB versus.; ASB, P=NS | Model adjustments:; - TEI: yes; Limitations:; - N/A; Funding:; Instituto Nacional de Ciencias Medicas y Nutricion Salvador Zubiran
Prospective cohort studies
Appelhans, 2017^113^; PCS, Study of Women’s Health Across the Nation (SWAN), U.S.; Analytic N=1,448; Included in meta-analysis: no; Study purpose: To test prospective associations between intakes of alcohol, energy-dense beverages, and low-calorie beverages and cardiometabolic risk in midlife women; Participant characteristics at baseline: Middleaged women; - Age: ~46y; - Female: 100%; - Race/ethnicity: 51% Non-Hispanic White; 25% African American; 24% Chinese/ Japanese; - SEP: 23% <$35K, 34% >$75K; - Anthropometry: NR; - Physical activity: 7.9 (scores range from 3 to 15 and higher score representing more frequent engagement in physical activity); - Smoking: 12.4% Current smoker; - Alcohol intake: NR; - Diet quality: NR; - TEI: ~1831 kcal/d; - Study beverage intake at baseline: Quantified in units of 355mL/d (~12oz/d); Mean (SD) :; Energy-dense, nonalcoholic beverages: 0.58 (1.01) Low-calorie teas, coffee, and diet cola: 1.10 (1.31); Inclusion: 42 to 52 years at enrollment, having an intact uterus and at least one ovary, not pregnant or lactating, not using oral contraceptives or reproductive hormone therapy, and reporting at least one menstrual cycle during the prior 3 months Exclusion: met criteria for the metabolic syndrome at baseline (n=372; 20%); Newark cohort (due to high attrition and lack of dietary data after Visit 5) | Exposure: Energy-dense, nonalcoholic beverages (includes Kool-aid, Hi-C, or other drinks with added vitamin C; Snapple, Calistoga, or sweetened bottled waters or iced teas; regular cola soft drinks; coffee or tea consumed with condiments that collectively yield an energy density ≥0.165 kcal/g); 1 svg=355 mL, 12 oz; Comparator: Continuous intake; Assessment methods and timing: Validated SWAN FFQ; intervieweradministered; assesses the usual frequency and portion sizes (1svg=355mL=~12oz); At baseline, 5y, 9y; converted to a single value that represents energy-adjusted usual intake across 9y; Outcomes and assessment methods: Waist circumference was measured to the nearest 0.1 cm with a measuring tape placed horizontally around the participant at the narrowest part of the torso; Abdominal obesity: Waist circumference; ≥80cm for Chinese/Japanese women and; ≥88cm for other ethnic/racial groups; At baseline, annually up to 14y (mean follow-up ~13y) | [underlined: Incident abdominal obesity], across 14y follow-up, OR (95% CI):; Intake: 0.66 (0.41, 1.06); Time*intake: 1.10 (1.03, 1.16) | Model adjustments:; - TEI: yes; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position (education), physical activity smoking; - Other: Study site, menopausal status, hormone therapy use, depressive symptoms; Limitations:; - Did not account for key confounders: anthropometry at baseline, diet quality; - Length of follow-up may not be consistent for all participants, No information on non-completers, No preregistered data analysis plan; Funding:; NIH
Auerbach, 2018^114^; PCS, Women’s Health Initiative, U.S.; Analytic N=49,106; Included in meta-analysis: yes; Study purpose: To examine whether 100% fruit juice consumption was associated with weight change in a large prospective cohort of postmenopausal women; Participant characteristics at baseline: Postmenopausal women; - Age: Mean (SD): 57.9 (4.1) y; - Female: 100%; - Race/ethnicity: 84% White; 8% Black; 3% Asian; 4% Hispanic; - SEP: 48% College degree or higher; 15% Annual household income ≥$75,000; - Anthropometry: Mean (SD), BMI: 26.2 (4.0) kg/m^2^; - Physical activity: Recreational physical activity level (MET-hours/wk): 4.3 (3.9); - Smoking: Current smoking 7.1%; - Alcohol intake: HEI diet quality score, Mean (SD): 67.9 (10.5); - Diet quality: HEI diet quality score, Mean (SD): 67.9 (10.5); - TEI: Mean (SD): 1636 (620) kcal/d; - Study beverage intake at baseline: Mean (SD): 0.30 (0.54) svg/d; Inclusion criteria: female; postmenopausal; age 50-79y;; Excluded: missing baseline weight, year 3 weight, baseline 100% fruit juice intake, year 3 100% fruit juice intake, baseline age >65y, BMI >35.0 kg/m2, implausible energy intake | Exposure: SSB intake (1 svg = 6 oz): regular soda and Tang®, Kool-Aid®, HiC®, or other <100% fruit juice drinks; Comparator: SSB intake (continuous; svg/d); Assessment methods and timing:; Validated FFQ; represents usual intake Baseline, 3y; analyzed as change across time; Outcomes and assessment methods:; - Weight measured using standardized protocol and calibrated scales; - Baseline, 3y follow-up | [underlined: Weight, lb/3-year change] per svg/d increase, Linear mixed effects model, B (95% CI):; TEI unadj: 0.58 (0.26, 0.90); TEI adj: 0.36 (0.29, 0.69); [underlined: Analysis with Multiple Imputation] (n = 4,397); TEI unadj: 0.58 (0.31, 0.85); TEI adj: 0.36 (0.34, 0.64); [underlined: Stratified by BMI group]; BMI 18.5-24.9 (n = 20,494):; TEI unadj: 0.63 (−0.04, 1.29); TEI adj: 0.51 (−0.17, 1.18); BMI 25.0-29.9 (n = 18,543):; TEI unadj: 0.49 (0.06, 0.92); TEI adj: 0.29 (−0.15, 0.73); BMI 30.0-34.9 (n = 9,588):; TEI unadj: 0.56 (−0.05, 1.18); TEI adj: 0.21 (−0.41, 0.83) | Model adjustments:; - TEI: yes and no; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position, anthropometry at baseline (BMI), physical activity, diet quality (3-year change in healthy eating index diet quality score), smoking; - Other: Hormone replacement therapy status; Limitations:; - Did not account for key confounders: anthropometry at baseline (weight); - No preregistered data analysis plan; Funding:; NHLBI; NIH
Barone-Gibbs, 2012^115^; PCS (secondary analysis of trial data), secondary analysis from trial (WOMAN: Women on the Move through Activity and Nutrition; control group only), U.S.; Analytic N=465 (6mo), 419 (48mo); Included in meta-analysis: no; Study purpose: To describe and compare associations between changes in eating behaviors and weight after 6 and 48 months; Participant characteristics at baseline: postmenopausal women with overweight or obesity enrolled in a diet and physical activity lifestyle intervention (data from control group); - Age: Mean (SD): 57 (2.9)y Range: 52-62y; - Female: 100%; - Race/ethnicity: 88% White; - SEP: NR; - Anthropometry: BMI Mean (SD): 30.8 (3.8), Range: 25-40;; Weight: ~82 kg; WC>80cm; - Physical activity: Leisure time physical activity: 11 MET-h/wk; - Smoking: NR; - Alcohol intake: Mean (SD): 4.1 (1.9) svg/d; - Diet quality: Mean (SD): 4.1 (1.9) svg/d; - TEI: NR; - Study beverage intake at baseline: Median (IQR): 0 (0-1) 12oz svg/d; Inclusion: aged 52–62 years and post-menopausal, BMI 25–39.9 kg/m2, WC >80 cm, BP <140/95 mmHg, LDL cholesterol from 100–160 mg/dL, no use of lipid lowering drugs, no history of cardiovascular disease or diabetes, and no physical limitations that would preclude physical activity; Exclusion: incomplete data | Exposure: SSB: Not further defined; Lifestyle change intervention w/ 10% weight loss goal (group-based weekly for 6mo, biweekly for 6mo, monthly for years 2-4): targeted reducing total, saturated, and trans fat along with cholesterol from meat, dairy, fats, oils, baked goods, and snacks; reducing energy intake; increasing foods high in soluble fiber; promotion of fruits, vegetables, and whole grains; promotion of sources of stanols/sterols and n-3 fatty acids; and increased physical activity; Comparator: SSB intake (continuous 12-oz svg/d); Control group (6 group seminars during year 1, 2-4 seminars years 2-4), content focused on general women’s health but not weight loss; Assessment methods and timing:; Validated questionnaire assessing regular eating behaviors in the past month At baseline, 6mo, 48mo, analyzed as change from baseline to 6mo and baseline to 48mo; Outcomes and assessment methods:; - Weight (Methods NR); - At baseline, 6mo, 48mo | [underlined: Change in weight over 6mo] by change in; SSB intake (n = 216), Linear regression,; Intervention (n = 238): β: 0.91, P=0.040; Control (n = 227): β: 0.57, P=0.120; Total sample (n = 465): β: 0.74, P=0.009; [underlined: Change in weight over 48 mo]; by change in SSB intake, Linear regression,; Intervention (n = 203): β: 1.53, P=0.072; Control (n = 216): β= 1.28, P=0.023; Total sample (n = 419): β: 1.25, P=0.011 | Model adjustments:; - TEI: no; - Key confounders: sex, anthropometry at baseline, physical activity (at 48mo not 6mo), diet quality (fruits & vegetables); - Other: N/A; Limitations:; - Did not account for key confounders: age, race/ethnicity, socioeconomic position, smoking; - Outcome assessment methods NR, No preregistered data analysis plan; Funding:; NHLBI
Barrio-Lopez, 2013^116^; PCS, Seguimiento Universidad de Navarra (SUN), Spain; Analytic N=8,157; Included in meta-analysis: yes; Study purpose: To prospectively assess the association between changes in the consumption of SSB and the incidence of metabolic syndrome and its components in a Spanish cohort of university graduates; Participant characteristics at baseline: adults; - Age: ~36y; - Female: 65%; - Race/ethnicity: NR; - SEP: 100% “highly educated participants”; - Anthropometry: BMI~22.7 kg/m^2^; - Physical activity: Leisure-time physical activity ~20.0 MET-hr/wk; - Smoking: ~24% Current smokers, ~26% Former smokers; - Alcohol intake: Mediterranean diet adherence by quintiles of SSB change:; Q1: 3.8+1.7, Q2: 4.0+1.8, Q3: 4.4+1.8, Q4: 4.0+1.8, Q5: 1.7+1.7; - Diet quality: Mediterranean diet adherence by quintiles of SSB change:; Q1: 3.8+1.7, Q2: 4.0+1.8, Q3: 4.4+1.8 Q4: 4.0+1.8, Q5: 1.7+1.7; - TEI: ~9929 kJ/d; - Study beverage intake at baseline: 4.9% consumed ≥1 svg/d; Inclusion: completed questionnaires up to 6 years of follow-up; Exclusion: ≥1 criteria for the MetS, extreme energy intake (<800 or >4000 kcal/d for men or <500 or >3500 kcal/d for women) | Exposure: SSB (sugar-sweetened carbonated colas and fruit-flavored carbonated sugar soft drinks; Not including artificially sweetened beverages, bottled fruit juice); Comparator: Baseline SSB intake, categorical; quintiles; Change in SSB intake, categorical; quintiles; - Quintile 1: those who decreased most of their consumption (ref); - Quintile 5 for those participants who increased most of their consumption; Assessment methods and timing: Validated semi-quantitative FFQ; frequency of SSB over past year (1svg=200mL); At baseline, 6y follow-up; Outcomes and assessment methods:; - Self-reported waist circumference (WC); measuring tape was provided with explanation about how to measure their own waist; - Weight change: methods NR; - At 6y and 8y follow-up | [underlined: Elevated waist circumference incidence at 6y] (≥94 cm in males, ≥80 cm in females), OR (95%CI):; Baseline SSB (quintile); Q1 (ref) versus Q5: 1.8 (1.01, 1.37); Other comparisons NR; Change in SSB quintile; Q1 (biggest decrease): ref; Q2: 1.3 (1.1, 1.6); Q3: 1.2 (1.0, 1.4); Q4: 2.1 (1.8, 2.6); Q5 (biggest increase): 2.3 (1.9, 2.7); P for trend<0.001; [underlined: Weight change (kg) over 6y]; Change in SSB; β (95% CI); Q1 (biggest decrease): ref; Q2: 0.5 (0.2, 0.9); Q3: 0.5 (0.2, 0.8); Q4: 1.1 (0.8, 1.4); Q5 (biggest increase): 1.3 (1.1, 1.6); P for trend<0.001 | Model adjustments:; - TEI: yes; - Key confounders: sex, age, anthropometry at baseline, physical activity, smoking, diet quality (adherence to Mediterranean dietary pattern, consumption of red meat, french fries, fast food); - Other: alcohol intake, soft drink intake at baseline; Limitations:; - Did not account for key confounders: race/ethnicity, socioeconomic position; - Waist circumference selfreported, Weight assessment methods NR, No preregistered data analysis plan, Low SSB consumption; Funding:; Spanish Government; Navarra Regional Government; University of Navarra
Bes-Rastrollo, 2008^118^; PCS, Nurses’ Health Study II, U.S.; Analytic N=50,026; Included in meta-analysis: no; Study purpose: To assess the long-term relation between changes in dietary energy density and age-related weight gain; Participant characteristics at baseline: Female nurses; - Age: Mean (SD): 36.5y (4.6); - Female: 100%; - Race/ethnicity: NR; - SEP: 100% Nurses; - Anthropometry: Mean (SD): BMI: 24.2 (5.0); Weight, kg: 65.9 (14.3); - Physical activity: MET-h/wk, Mean (SD): 20.4 (26.4); - Smoking: Current: 11%; - Alcohol intake: Dietary ED, kcal/g (food only): 1.2 (0.4); Dietary ED, kcal/g (food+beversus): 1.1 (0.3); Food group intake, Mean (SD):; Vegetables, g/d: 159 (99); Fruit, g/d: 176 (118); Other macronutrient and food group intakes reported in paper; - Diet quality: Dietary ED, kcal/g (food only): 1.2 (0.4); (food+bev): 1.1 (0.3); Vegetables, g/d: 159 (99); Fruit, g/d: 176 (118); - TEI: Mean (SD), kcal/d: 1771 (522); - Study beverage intake at baseline: High-calorie carbonated soda intake at baseline, Mean (SD), 111.7 (210.6) g/d; Exclude: missing dietary (completely missing or >9 missing items), physical activity, weight, or follow-up data; unreasonable energy intakes; history of diabetes or CVD; cancer; pregnancy | Exposure: Cola, caffeine-free cola, other carbonated beverages, punch; Comparator: Categorical intake (tertiles of change); Assessment methods and timing:; Self-administered semi-quantitative FFQ;; Represents intake during previous year Baseline, 8y; analyzed as tertiles of change; Outcomes and assessment methods:; - Self-reported; - Baseline, 8y | [underlined: Weight change over 8y, kg], β (95% CI) Data NR, Figure only; Highest tertile of change in SSB intake versus. lowest tertile: Regular soda, caffeine-free soda, and fruit punches were associated with greater weight gain (data NR) | Model adjustments:; - TEI: no; - Key confounders: sex, age, anthropometry at baseline, physical activity, smoking; - Other: Postmenopausal hormone use, oral contraceptive use; Limitations:; - Did not account for key confounders: race/ethnicity, SEP, diet quality; - Exposures not well defined and FFQ varied over time; No info on non-completers; Selfreported weight; No preregistered data analysis plan; Funding:; NIH; Spanish Ministry of Education; Fundacion Caja Madrid; Amigos de la Universidad de Navarra; AHA Established Investigator Award
Bes-Rastrollo, 2006^117^; PCS, Seguimiento Universidad de Navarra (SUN), Spain; Analytic N=7,194; Included in meta-analysis: yes; Study purpose: To assess whether the consumption of sweetened drinks and other food items increased the likelihood of weight gain in a Mediterranean population; Participant characteristics at baseline: Adult university graduates; - Age: Mean ~36y; - Female: ~60%; - Race/ethnicity: NR; - SEP: 100% University graduates; - Anthropometry: Mean~67kg; - Physical activity: Mean~19 MET-hr/wk; - Smoking: ~25% current smokers; 27% former smoker; - Alcohol intake: Range of means among quintiles Fiber intake: 24-42 g/d; Intake of hamburgers, pizza, sausages: 17-30 g/d; Snacking between meals: 28-50%; - Diet quality: Range of means among quintiles Fiber intake: 24-42 g/d; Intake of hamburgers, pizza, sausages: 17-30 g/d; Snacking between meals: 28-50%; - TEI: Mean~2575 kcal/d; - Study beverage intake at baseline: Baseline SSSD intake: ~20% consumed ≥84 mL/d; Baseline sweetened fruit juice intake: ~20% consumed ≥186 g/d; Included: SUN cohort participants who had already been followed-up for ≥2 y.; Excluded: extremely low or high values for total energy intake (<800 or >4200 kcal/d for men and<600 or >3500 kcal/d for women), missing values for the variables of interest, biologically implausible values for weight or height | Exposure: Sugar-sweetened soft drinks (SSSD); sweetened fruit juice; Comparator: SSB intake (categorical, quintiles, mL/d); Weight gain ≥3 kg in previous 5y; Q1 (ref): <5.5; Q2: 5.5-17.6; Q3: 17.7-33.3; Q4: 33.4-87.4; Q5: ≥87.5; Weight gain <3 kg in previous 5y; Q1 (ref): <4.0; Q2: 4.0-14.8; Q3: 14.9-27.8; Q4: 27.9-80.2; Q5: ≥80.3; Sweetened fruit juice intake (categorical, quintiles, g/d); Q1 (ref): <13.3; Q2: 13.3-26.7; Q3: 26.8-57.1; Q4: 57.2-185.7; Q5: ≥185.8; Assessment methods and timing: Validated semi-quantitative FFQ Baseline; Outcomes and assessment methods:; - Weight was self-reported; - Weight gain during follow-up defined categorically (any increase ≥ 1kg during follow-up) and continuously (difference between weight at baseline and follow-up); - Baseline, median 28.5mo follow-up | SSSD Intake; [underlined: Weight gain over 2y+] (categorical: any weight gain versus. none), OR (95% CI), Logistic regression; By quintile of intake, adjusted for TEI: Weight gain ≥3 kg in 5y period before baseline (n=2320); Q1 (ref),; Q2: 1.37 (1.04, 1.81), Q3: 1.24 (0.93, 1.64),; Q4: 1.34 (1.01, 1.78), Q5: 1.55 (1.16, 2.07),; P for trend=0.018; [underlined: Weight gain <3kg in 5y] period before baseline (n=4874); Q1 (ref),; Q2: 1.24 (1.02, 1.50), Q3: 1.21 (1.00, 1.48),; Q4: 0.99 (0.82, 1.21), Q5: 1.08 (0.89, 1.32),; P for trend=0.611; P for interaction (SSSD intake and weight gain in previous 5y)=0.06; [underlined: Weight gain over 2y+, kg] (continuous), β (95% CI), Linear regression; By quintile of intake, adjusted for TEI: Weight gain ≥3 kg in 5y period before baseline; Q1 (ref),; Q2: NS, data NR, Q3: NS, data NR,; Q4: 1.0 (0.4, 1.6), Q5: 1.2 (0.6, 1.8),; P for trend=0.001; [underlined: Weight gain <3kg in 5y] period before baseline; Q1 (ref) versus Q2-Q5: NS, data NR; Sweetened fruit juice intake; [underlined: Weight gain] (categorical: any weight gain versus. none), OR (95% CI), Logistic regression; By quintile of intake, adjusted for TEI:; Q1 (ref); Q2: 0.99 (0.84, 1.17), Q3: 1.08 (0.91, 1.28); Q4: 1.08 (0.92, 1.27), Q5: 1.16 (0.99, 1.36); P for trend=0.039 | Model adjustments:; - TEI: yes and no; - Key confounders: sex, age, anthropometry at baseline, physical activity, smoking, diet quality (fiber intake, fast food intake (hamburgers, pizza, sausages)); - Other: milk intake; alcohol intake; television watching; snacking between meals; weight gain ≥3 kg in the past 5y; Limitations:; - Did not account for key confounders: race and/or ethnicity, socioeconomic position; - Exposure data only measured at baseline; No information on non-completers; Weight was self-reported; No preregistered data analysis plan; Funding:; Department of Health of the Navarre Regional Government; Spanish Ministry of Health
Boggs, 2013^119^; PCS, Black Women’s Health Study (BWHS), U.S.; Analytic N=19,479; Included in meta-analysis: yes; Study purpose: To investigate the relation of intakes of sugar-sweetened soft drinks and specific types of restaurant foods to obesity in the Black Women’s Health Study; Participant characteristics at baseline: African American women; - Age: ~31y (21-39y); - Female: 100%; - Race/ethnicity: 100% African American; - SEP: ~50% ≥16y education; - Anthropometry: BMI: ~24 (18.5-29.9); - Physical activity: vigorous ≥5hr/wk ~18%; - Smoking: Current smoker ~13%; - Alcohol intake:; Prudent dietary pattern Q5, (high intake of fruit and vegetables) by intake of SSB: <1 drink/mo: 38%, 1-7/mo: 22%, 2-6/wk: 10%, 1/d: 3%; Western dietary patter Q5,% (high intake of meat and fried foods): <1 drink/mo: 12%, 1-7/mo: 20%, 2-6/wk: 26%, 1/d – 24%; - Diet quality: Prudent dietary pattern Q5, (high intake of fruit and vegetables) by intake of SSB: <1/mo: 38%, 1-7/mo: 22%, 2-6/wk: 10%, 1/d: 3% Western dietary pattern Q5,% (high intake of meat and fried foods): <1 drink/mo: 12%, 1-7/mo: 20%, 2-6/wk: 26%, 1/d: 24%; - TEI: NR; - Study beverage intake at baseline: ≥1/d: 16%; Inclusion: 21-39y, BMI 18.5-29.9 kg/m2 at baseline (n=22,879); Exclusion: pregnant at baseline, history of cancer (except nonmelanoma skin cancer), cardiovascular disease, or gastric surgery, >10 items blank on the baseline FFQ, implausible energy intake values (<400 or >3800 kcal), or missing weight on all follow-up questionnaires | Exposure: Regular soft drinks (not diet soda); Comparator: SSB, categorical: <1 drink/mo (ref); 1-7/mo; 2-6/wk; 1/d; ≥2/d; Assessment methods and timing:; Validated FFQ (self-administered modified version of the Block-National Cancer Institute FFQ); specified frequency and portions (1svg=12oz); At baseline (1995), 6y (2001);; Baseline intake assessed in relation to obesity risk from 1995–2001, and intake in 2001 assessed in relation to obesity risk from 2001–2009; analyzed in same model; Outcomes and assessment methods:; - Height and weight: self-report by questionnaire; - BMI calculated; - Obesity: BMI≥30 kg/m2; - At baseline (1995), every 2y up to 14y (2009) | [underlined: Incident obesity], HR (95%CI) <1 drink/mo (ref); 1-7/mo: 1.05 (0.98, 1.12); 2-6/wk: 1.03 (0.95, 1.11); 1/d: 1.08 (0.98, 1.20); ≥2/d:1.12 (1.00, 1.25); P-trend= 0.07; [underlined: Stratified by baseline age and BMI]; HR (95%CI):; Baseline age 21-29y & BMI 18.5-24.9:; <1 drink/mo (ref); 1-7/mo: 1.29 (1.07, 1.56); 2-6/wk: 1.40 (1.14, 1.73); 1/d: 1.45 (1.10, 1.92); ≥2/d: 1.32 (0.96, 1.83); P-trend= 0.01; Baseline age 21-29y & BMI 25.0-29.9:; <1 drink/mo (ref); 1-7/mo: 0.98 (0.86, 1.12); 2-6/wk: 0.98 (0.84, 1.13); 1/d: 1.08 (0.89, 1.31); ≥2/d: 1.14 (0.93, 1.40); P-trend= 0.19; Baseline age 30-39y & BMI 18.5-24.9:; <1 drink/mo (ref); 1-7/mo: 0.95 (0.80, 1.13); 2-6/wk: 0.97 (0.80, 1.19); 1/d: 0.80 (0.59, 1.10); ≥2/d: 1.06 (0.75, 1.50); P-trend= 0.68; Baseline age 30-39y & BMI 25.0-29.9:; <1 drink/mo (ref); 1-7/mo: 1.03 (0.93, 1.13); 2-6/wk: 0.96 (0.86, 1.07); 1/d: 1.03 (0.89, 1.19); ≥2/d: 1.02 (0.87, 1.20) P-trend= 0.99 | Model adjustments:; - TEI: no; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position (education), anthropometry at baseline, physical activity, diet quality (western and prudent dietary patterns), smoking, parity; - Other: alcohol intake, geographic region; Limitations:; - Did not account for key confounders:; - Weight and height self-reported, Length of follow-up differed among participants, No preregistered data analysis plan; Funding:; Aetna Foundation; NCI
Bundrick, 2014^120^; PCS, Obesity and Diabetes Clinical Research; Section (NIDDK), U.S.; Analytic N=85; Included in meta-analysis: no; Study purpose: To determine whether soda consumption predicts weight gain or changes in glucose regulation over time; Participant characteristics at baseline: adults; - Age: 34.3 (8.9); - Female: 37%; - Race/ethnicity: 28% White ; 64% Native American; - SEP: NR; - Anthropometry: BMI 32.5 (7.4) kg/m2; Body fat 31.6 (8.6)%; - Physical activity: NR; - Smoking: NR; - Alcohol intake: NR; - Diet quality: NR; - TEI: ~4400 kcal/d; - Study beverage intake at baseline: kcal/d mean: 379 (252); Inclusion: complete follow up data; Exclusion: type 2 diabetes, nonphysiologic weights | Exposure: SSB: energy from soda and juice; Soda: sweetened carbonated beverages only; Comparator: kcal, continuous; Assessment methods and timing: After admission to research unit, subjects were fed a weight-maintaining diet for 3 days consisting of 20% of energy from protein, 30% from fat, and 50% from carbohydrate. During final 3 days of admission, subjects were asked to selfselect food from a computer-operated vending machine. Water, coffee, 2% milk, orange juice, apple juice, and six 12-oz cans of the subject’s soda choice were available each day. Subjects were allowed free access to vending machine and asked to mirror their usual eating behaviors. They were instructed to eat alone and in the vending room, which contained a microwave for any necessary food preparation. They were told to return all wrappers and uneaten food to the vending machine for weighing.; Baseline; Outcomes and assessment methods:; - Height was measured to the nearest centimeter using a stadiometer; - Weight was measured using a calibrated digital scale; - Baseline, follow-up (Mean 2.5±2.1y; range 6mo to 9.9y) | [underlined: Weight change, kg], Spearman correlation; Soda energy (n=85): 0.21, P=0.04; SSB energy (soda+juice) (n=59): 0.23, P=0.08 | Model adjustments:; - TEI: no; - Key confounders: sex, age, race/ethnicity, anthropometry at baseline; - Other: follow up time; Limitations:; - Did not account for key confounders: socioeconomic position physical activity, diet quality, smoking; - Exposure data only measured at baseline, Differences in energy from soda, and SSBs between completers and noncompleters, Registry does not include data analysis plan; did not report results for BMI or body composition despite methods reporting these measures; Funding:; NIDDK
Buso, 2022^121^; PCS, Lifelines Cohort Study, The Netherlands; Analytic N=78,286; Included in meta-analysis: yes; Study purpose: To examine prospective doseresponse associations of SSB, low/no-calorie beverages, and fruit juice with body weight-related outcomes; Participant characteristics at baseline: Adults; - Age: Mean (SD): 46y (13); - Female: 60%; - Race/ethnicity: NR; - SEP: Education: 4% Low (<secondary school): 65% Intermediate (secondary school but <Bachelor’s), 31% High (Bachelor, Master, or PhD); - Anthropometry: Mean (SD): Weight (kg): 79.5 (15), BMI: 26 (4.2), WC (cm): 90.1 (12.2) BMI <25: 45%; ≥25: 55%; - Physical activity: METs min/wk: Median [25th, 75th percentile], Intense: 0 [0, 630], Moderate: 1,665 [806, 2,948], Sedentary (min/wk): 840 [630, 1,260]; - Smoking %: Never: 47; Former: 35, Current: 18; - Alcohol intake: Median (25th-75th%) serv/d; SSB: 0.11 (0.0, 0.61); - Diet quality: Median (25th-75th%) serv/d; SSB: 0.11 (0.0, 0.61); - TEI: Median [25th, 75th percentile]: 1,977 [1,640, 2,380]; - Study beverage intake at baseline:; SSB: Median [25th, 75th percentile] 0.1 [0.0, 0.6] svg/day; 62% consumed SSB; Juice: Median [25th, 75th percentile] 0.2 [0.0, 0.6] svg/day; 77% consumed fruit juice; Excluded: severe psychiatric or physical illness, limited life expectancy (<5 years), insufficient knowledge of Dutch language, unreliable dietary data (TEI <500 or >3,500 kcal/day for women and <800 and >4000 for men), missing data on body weight change, waist circumference change, or covariates; Included: available data on body weight and waist circumference change | Exposure: Soda sugar drinks or lemonade (both carbonated and noncarbonated; & (as separate exposure); 100% fruit juice and other fruit drinks; Comparator: Continuous intake (serv/d), Categorical intake (0 svg/d: REF; ≤1 svg/d; 1-2svg/d; >2 svg/d; Assessment methods and timing: Semi-quantitative 110-item FFQ with 150 m7l as standard serving; Baseline (2006-2013); Outcomes and assessment methods: Height, weight, and waist circumference measured by trained professionals; change in weight and WC calculated by weight follow-up – weight baseline)/years of follow-up and WC follow-up – WC baseline)/years of follow-up; overweight/obesity were defined by a BMI 25 kg/m2 at follow-up and abdominal obesity with a waist circumference >94 cm for men and >80 cm for women Baseline (2006-2013) and 1-9y later (Median: 4y) | [underlined: Waist circumference change, cm/y], by baseline SSB intake, β (SE), Linear regression:; TEI not adjusted: 0.03 (0.01); TEI adjusted: 0.04 (0.01); Stratified analyses (TEI adjusted): BMI (<25, ≥25): p=0.13; Sex: p=0.32, Age (<46y, ≥46): p=0.61; Dose-response associations, β (SE), restricted cubic spline analysis, TEI adjusted:; 0 serv/d: REF; ≤1 serv/d: −0.03 (0.02); 1-2serv/d: −0.01 (0.03); >2 serv/d: 0.09 (0.04); P non-linear = 0.24 Stratified analyses (TEI adjusted): BMI: p<0.001; Sex: p<0.01; Age: p=0.59; [underlined: Abdominal obesity incidence] by baseline SSB intake, IPR (95% CI), Cox proportional hazards regression (6,896 cases in 31,292 without abdominal obesity at baseline): TEI not adjusted: 1.01 (0.99, 1.04); TEI adjusted: 1.02 (0.99, 1.05); Stratified analyses (TEI adjusted): Sex: p=0.71, Age (<46y, ≥46): p=0.33; Dose-response associations, IPR (95% CI), restricted cubic spline analysis, TEI adjusted:; 0 serv/d: REF; ≤1 serv/d: 0.99 (0.95, 1.04); 1-2serv/d: 1.01 (0.93, 1.08); >2 serv/d: 1.06 (0.95, 1.16); P non-linear = 0.70; Stratified analyses (TEI adjusted): BMI: p<0.001; Sex: p=0.90; Age: p=0.57; [underlined: Waist circumference change, cm/y], by baseline fruit juice intake, β (SE), Linear regression:; TEI not adjusted: −0.01 (0.01); TEI adjusted: −0.00 (0.01); Stratified analyses (TEI adjusted): BMI (<25, ≥25): p=0.11; Sex: p=0.13, Age (<46y, ≥46): p=0.52; Dose-reponse associations, β (SE), restricted cubic spline analysis, TEI adjusted:; 0 serv/d: REF; ≤1 serv/d: −0.06 (0.02); 1-2serv/d: −0.03 (0.03); >2 serv/d: −0.02 (0.03); P non-linear = 0.01; Stratified analyses (TEI adjusted): BMI: p=0.21; Sex: p=0.20; Age: p=0.44; [underlined: Abdominal obesity incidence] by baseline fruit juice intake, IPR (95% CI), Cox proportional hazards regression (6,896 cases in 31,292 without abdominal obesity at baseline):; TEI not adjusted: 1.03 (0.99, 1.06); TEI adjusted: 1.03 (1.00, 1.07); Stratified analyses (TEI adjusted): Sex: p=0.99 Age (<46y, ≥46): p=0.88; Dose-response associations, IPR (95% CI), restricted cubic spline analysis, TEI adjusted:; 0 serv/d: REF; ≤1 serv/d: 0.99 (0.94, 1.04); 1-2serv/d: 1.05 (0.97, 1.13); >2 serv/d: 1.04 (0.90, 1.21); P non-linear = 0.49; Stratified analyses (TEI adjusted): Sex: p=0.92; Age (<46y, ≥46): p=0.41; [underlined: Weight change, kg/y], by baseline SSB intake, β (SE), Linear regression: TEI not adjusted: 0.02 (0.01);; TEI adjusted: 0.02 (0.01); Stratified analyses (TEI adjusted): BMI: p<0.001; Sex: p=0.11, Age: p=0.46; Dose-response associations, β (SE), restricted cubic spline analysis, TEI adjusted:; 0 serv/d: REF; ≤1 serv/d: −0.04 (0.01); 1-2serv/d: −0.03 (0.02); >2 serv/d: 0.04 (0.03); P non-linear = 0.04; Stratified analyses (TEI adjusted): BMI: p<0.001; Sex: p<0.001; Age: p=0.58; [underlined: Overweight/Obesity incidence] by baseline SSB intake, IPR (95% CI), Cox proportional hazards regression (4,884 cases in 35,202 normal BMI at baseline):; TEI not adjusted: 1.02 (0.99, 1.05); TEI adjusted: 1.03 (1.00, 1.06); Stratified analyses (TEI adjusted): Sex: p=0.76, Age: p=0.52; Dose-response associations, IPR (95% CI), restricted cubic spline analysis, TEI adjusted:; 0 serv/d: REF; ≤1 serv/d: 0.94 (0.88, 1.00); 1-2serv/d: 0.92 (0.83, 1.01); >2 serv/d: 1.16 (1.04, 1.28); P non-linear = 0.27; Stratified analyses (TEI adjusted): Sex: p=0.79; Age: p=0.38; [underlined: Weight change, kg/y], by baseline fruit juice intake, β (SE), Linear regression:; TEI not adjusted: −0.02 (0.01); TEI adjusted: −0.02 (0.01); Stratified analyses (TEI adjusted): BMI (<25, ≥25): p=0.01; Sex: p=0.05, Age: p=0.22; Dose-response associations, β (SE), restricted cubic spline analysis, TEI adjusted: 0 serv/d: REF; ≤1 serv/d: −0.07 (0.01); 1-2serv/d: −0.07 (0.01); >2 serv/d: −0.09 (0.05); P non-linear < 0.001; Stratified analyses (TEI adjusted): BMI: p<0.01; Sex: p=0.03; Age: p=0.12; [underlined: Overweight/Obesity incidence] by baseline fruit juice intake, IPR (95% CI), Cox proportional hazards regression (4,884 cases in 35,202 normal BMI at baseline):; TEI not adjusted: 0.99 (0.95, 1.03); TEI adjusted: 1.00 (0.96, 1.04); Stratified analyses (TEI adjusted): Sex: p=0.30, Age: p=0.97; Dose-response associations, IPR (95% CI), restricted cubic spline analysis, TEI adjusted:; 0 serv/d: REF; ≤1 serv/d: 0.89 (0.83, 0.95); 1-2serv/d: 0.94 (0.84, 1.03); >2 serv/d: 1.00 (0.82, 1.18); P non-linear = 0.02; Stratified analyses (TEI adjusted): Sex: p=0.76; Age: p=0.81 | Model adjustments:; - TEI: yes and no; - Key confounders: sex, age, socioeconomic position, anthropometry at baseline, physical activity, diet quality, smoking; - Other: alcohol intake, history of disease, sedentary behavior; Limitations:; - Did not account for key confounders: race and/or ethnicity; - Exposure data only measured at baseline; No information on non-completers; No preregistered data analysis plan; Funding:; European Union’s Horizon 2020 research and innovation programme
Carroll, 2018^123^; PCS, Place and Metabolic Syndrome (PAMS); Project, Australia; Analytic N=1,630; Included in meta-analysis: no; Study purpose: To assess spatial associations between local descriptive norms for overweight/obesity and insufficient fruit intake (spatially-specific local prevalence), and individuallevel dietary intakes (fruit, vegetable and sugary drinks) and 10-year change in BMI and HbA1c.; Participant characteristics at baseline: adults; - Age: ~51y; - Female: 51%; - Race/ethnicity: NR; - SEP: 13% University graduate; - Anthropometry: mean BMI: ~25; - Physical activity: NR; - Smoking: current smoker 18%; - Alcohol intake: Fruit intake (daily count of servings) ~ 1.5 (1.0); Vegetable intake (daily count of servings) ~2.5 (1.4); - Diet quality: Fruit intake (daily count of servings) ~ 1.5 (1.0); Vegetable intake (daily count of servings) ~2.5 (1.4); - TEI: NR; - Study beverage intake at baseline: Drinks sugary drinks; % of sample: ~55%; Inclusion: Households within the NWAHS region (defined by postcode) were randomly selected from the Australian Electronic White Pages telephone directory and the adult (18 years or over) who most recently had their birthday asked to participate in the study; Exclusion: NR | Exposure: soft drink, cordial or sports drinks; Comparator: Sugary drink intake (categorical; frequency/wk); Rarely/never (0/wk) >1/wk; Assessment methods and timing:; Weekly frequency of sugary drink consumption using Computer-Assisted; Telephone Interviews (CATI); not validated; Baseline (2007); Outcomes and assessment methods: Height measured a wall-mounted stadiometer; Weight measured using standard digital scales; BMI calculated as kg/m2; At baseline (2001), and ~8y follow-up 2005-06, 2008-10) | [underlined: Change in BMI], SEM, β (95% CI) 0/wk (ref) versus; >0wk: 0.041 (0.008, 0.075), P=0.016 | Model adjustments:; - TEI: no; - Key confounders: sex, age, socioeconomic position (education), anthropometry at baseline, smoking; - Other: Marital status; Limitations:; - Did not account for key confounders: race and/or ethnicity, physical activity, diet quality; - Exposure data only measured at one time, Exposure is based on frequency, not amount consumed, Exposure data collection tool not validated, No preregistered data analysis plan; Funding:; National Health and Medical Research Council
Castellana, 2020^124^; PCS, Multicenter Italian study on Cholelithiasis, third examination (MICOL3) and GreatAGE, Italy; Analytic N=114; Included in meta-analysis: no; Study purpose: To analyze the relation of food group intake to clinical chemical indicators of health, and also to compare the food group intake with healthy well-known diet indices; Participant characteristics at baseline: older adults; - Age: mean (SD): 65.95 (6.59)y; - Female: 42%; - Race/ethnicity: NR; - SEP: NR; - Anthropometry: BMI, Mean (SD): 29.83 (5.04) kg/m2; - Physical activity: NR; - Smoking: NR; - Alcohol intake: Grams/day, Mean (SD); Leafy vegetables 63.14 (60.53); Fruiting vegetables 93.24 (74.51); Root vegetables 7.81 (20.72); Other vegetables 74.65 (64.43); Fruit 595.53 (405.44); - Diet quality: Grams/day, Mean (SD); Leafy vegetables 63.14 (60.53); Fruiting vegetables 93.24 (74.51); Root vegetables 7.81 (20.72); Other vegetables 74.65 (64.43); Fruit 595.53 (405.44); - TEI: Mean (SD): 2182.76 (773.06) kcal/d; - Study beverage intake at baseline: NR; Included: age 65+ in 2015 (baseline for GreatAGE), without impaired health indicators at baseline, participated in both MICOL3 and reatAGE cohorts; Excluded: missing information for outcomes or covariates | Exposure: “caloric drinks”: intake from Coca-Cola, Aranciata, and Chinotto (single foods used in FFQ); Comparator: Amount of intake (gram/day), standardized to energy intake of 2000 kcal/d; Assessment methods and timing:; Validated FFQ- 85 items considered to reflect regional diet; Baseline (MICOL3 - 2005-2006); Outcomes and assessment methods: Height and weight: valid measure by study staff.; M3 2005-2006 and greatAGE 2012-2018 (mean follow-up ~7.5y) | [underlined: BMI gain >1.5 kg/m]^2^ in GreatAGE (20122018) based on baseline SSB intake; linear regression; P=0.779 | Model adjustments:; - TEI: yes; - Key confounders: sex, age, socioeconomic position (years of education), anthropometry at baseline, smoking; - Other: N/A; Limitations:; - Did not account for key confounders: race and/or ethnicity, physical activity, diet quality; - Start of follow-up and exposure do not coincide; Exposure not well defined; Exposure data only measured at baseline; High missing data (84.5%) with no information on non-completers; No preregistered data analysis plan; Funding:; Italian Ministry of Health
Chen, 2009^125^; PCS (secondary analysis of trial data), Secondary analysis of PREMIER randomized trial, U.S.; Analytic N=810; Included in meta-analysis: yes; Study purpose: To examine how changes in beverage consumption affect weight change among adults; Participant characteristics at baseline: adults enrolled in an 18mo behavioral intervention trial to lower BP; - Age: Mean (SD) = 50 (8.9) y, Range 25-79y; - Female: 62%; - Race/ethnicity: 64% Non-Hispanic White; 34% African American; 1% Other; - SEP: 57% college degree or above; 70% annual household income >$45,000, 65% married; - Anthropometry: BMI Mean (SD): 33.1 (5.8) kg/m^2^; 65% BMI ≥30, 29% BMI 25.0-29.9, 5% BMI <25; - Physical activity: EER Mean (SD) 33.7 (2.9) kcal/kg∙d; - Smoking: 4.8% current smokers; - Alcohol intake: Liquid calorie intake, Mean (SD): 356 (237) kcal/d; % of total energy intake from liquid calories, Mean (SD): 19 (11.5); - Diet quality: Liquid calorie intake, Mean (SD): 356 (237) kcal/d; % of total energy intake from liquid calories, Mean (SD): 19 (11.5); - TEI: NR; - Study beverage intake at baseline: SSB intake at baseline, Mean (SD): 310.5 (354.8) mL/d; Included: adults with prehypertension or stage 1 hypertension (systolic BP 120-159 mmHg and diastolic BP 80-95 mmHg).; Excluded: individuals who routinely used antihypertensive medications, weight loss medication, or oral steroids, diabetes, history of a cardiovascular event, CHF, current symptoms of angina or PVD, cancer diagnosis or treatment in past 2y, renal insufficiency, or psychiatric hospitalization within the past 2y | Exposure: SSBs (regular soft drinks, fruit drinks, fruit punch, or any other highcalorie beverage sweetened with sugar); 1 svg = 12 fl oz or 355 mL; Comparator: Continuous intake (12-oz svg/d) and categorical intake (tertiles, ml/d); Assessment methods and timing:; Two 24h dietary recalls (1 weekday and 1 weekend day) via telephone interviews using multiple-pass and portion size estimation aids; At baseline, 6mo, and 18mo; analyzed as change over time; Outcomes and assessment methods: Weight measured using calibrated scale At baseline, 6mo, and 18mo | [underlined: Weight loss (kg)] according to reduction in SSB intake by 1 svg/d, β (95% CI); At 6mo: 0.49 (0.11, 0.82), p=0.006; At 18mo: 0.65 (0.22, 1.09), p=0.003; [underlined: Stratified analyses]:; At 6mo:; Race: White 0.38, p<0.05; Black 0.59, p<0.05; Sex: Men 0.27, NS; Women 0.70, p<0.05; Baseline BMI: <30 kg/m2, 0.22, NS; ≥30 kg/m2, 0.59, p<0.05; Age: <50y, 0.48, p<0.05; ≥50y, 0.24, NS At 18mo:; Race: White 0.81, p<0.05; Black 0.54, NS; Sex: Men 0.38, NS; Women 1.08, p<0.05; Baseline BMI: <30 kg/m2, 0.43, NS; ≥30 kg/m2, 1.08, p<0.05; Age: <50y, 0.60, NS; ≥50y, 0.72, p<0.05; No test for interaction (sex/SSB intake, baseline BMI/SSB intake, age/SSB intake) was statistically significant.; [underlined: Weight loss (kg) at 6mo] according to tertile of 6mo change in SSB intake (T1 had greatest reduction in SSB intake); T1: −4.8 kg, T2: −4 kg, T3: −2.4 kg; T1 versus T2: 0.7, P=0.006; T1 versus T3: 2.4, P<0.001; p-trend (dose response)<0.001; [underlined: Weight loss (kg) at 18mo] according to tertile of 18mo change in SSB intake; T1: −5.2 kg; T2: −3.5 kg; T3: −1.5 kg; T1 versus T2: 1.6, p<0.001; T1 versus T3: 3.6, p<0.001; p-trend<0.001 | Model adjustments:; - TEI: yes; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position, anthropometry at baseline, physical activity, diet quality, smoking; - Other: intervention group; Limitations:; - Did not account for key confounders:; - No preregistered data analysis plan; Funding:; NHLBI; NIH; Center for Human Nutrition, Johns Hopkins Bloomberg School of Public Health; NICHD
Chen, 2010^126^; PCS (secondary analysis of trial data), Secondary analysis of PREMIER randomized trial, U.S.; Analytic N=810; Included in meta-analysis: no; Study purpose: To determine the relationship between changes in SSB consumption and changes in blood pressure among adults; Participant characteristics at baseline: adults in 18mo behavioral intervention trial to lower BP; - Age: Mean (SD) = 50 (8.9) y, Range 25-79y; - Female: 62%; - Race/ethnicity: 64% Non-Hispanic White; 34% African American; 1% Other; - SEP: Education: college degree or above: 57%; Household income >$45,000/y, 70%; - Anthropometry: Weight Mean (SD): 210 (41.5) lb BMI, 33.1 (5.8) kg/m2; WC, 107.6 (15.2) cm; - Physical activity: Time spent on moderate or hard activity, Median: 173.5min/wk; - Smoking: Current: 5%; - Alcohol intake: Mean (SD) by quartile of SSB intake:; Fruit & vegetables: Q1: 4.7 (2.3), Q2: 4.5 (2.3), Q3: 4.5 (2.3), Q4: 4.2 (2.4); - Diet quality: Mean (SD) by quartile of SSB intake:; Fruit & vegetables: Q1: 4.7 (2.3), Q2: 4.5 (2.3), Q3: 4.5 (2.3), Q4: 4.2 (2.4); - TEI: Mean (SD), 1904.5 (625.2) kcal/d; - Study beverage intake at baseline: SSB intake (fl oz/d), Mean (SD), 10.5 (11.9); Median (Range), 8.5 (0-75.4); Include: Age 25-79y; SBP 120–159 and DBP 80– 95 mmHg; BMI 18.5-45; not taking medication for hypertension, BP, insulin, oral hypoglycemic agents, psychosis, manic-depressive illness, or weight loss; CVD; cancer; renal insufficiency; glucose ≥160 or fasting glucose ≥126 mg/dL; psychiatric hospitalization w/in 2y; >21 alcoholic drinks/wk or binge drinking; pregnant, breast feeding, or planning pregnancy; participation in other clinical trial; family member who’s a PREMIER participant or staff member | Exposure: SSB (carbonated or uncarbonated drinks that were sweetened with sucrose or high-fructose corn syrup, including regular soft drinks, fruit drinks, lemonade, fruit punch, and other sweetened beverages, but excluding diet drinks defined as carbonated or uncarbonated drinks sweetened with artificial/noncaloric sweeteners); Comparator: Categorical intake, tertiles (oz/d); Assessment methods and timing:; Two multiple-pass 24hr dietary recalls via telephone interviews; At baseline, 6mo, 18mo; analyzed as change over time; Outcomes and assessment methods:; Weight measured using calibrated scale At baseline, 18mo | [underlined: Weight change, lb], Mean (SD); Change from baseline to 18mo by change in SSB intake at 18mo; Tertile 1: −3.9 (9.2); Tertile 2: −6.4 (12.7); Tertile 3: −10.9 (16.4); P for trend <0.001 | Model adjustments:; - TEI: no; - Key confounders: anthropometry at baseline; - Other: Medications; Limitations:; - Did not account for key confounders: sex; age; race/ethnicity; SEP; physical activity; smoking; diet quality; - Start of follow-up and exposure do not coincide; No preregistered data analysis plan; Funding:; NHLBI; School of Public Health, Louisiana State University Health Science Center; Center for Human Nutrition, Johns Hopkins Bloomberg School of Public Health
Cleland, 2018^127^; PCS, Childhood Determinants of Adult Health study H1 (2004-06) and H2 (2009-10), Australia; Analytic N=1,068; Included in meta-analysis: no; Study purpose: To determine whether longitudinal associations between young adults’ TV viewing and BMI are explained by changes in TV-related food and beverage consumption and/or leisuretime physical activity over 5 years among young adults; Participant characteristics at baseline: adults; - Age: 31.5 (2.6) y; - Female: NR; - Race/ethnicity: NR; - SEP: ~55% university degree; - Anthropometry: BMI ~25 kg/m2; Weight Status: 56% Healthy, 31% Overweight, 13% Obesity; - Physical activity: ~101 mins/wk; - Smoking: 81% non-smoker; - Alcohol intake: NR; - Diet quality: NR; - TEI: NR; - Study beverage intake at baseline: TV-related soft drink intake, % of sample: None: ~48%; ≥5 times/wk: ~9%; Inclusion: participated in the 1985 ASHFS school children aged 7–15 years from 109 public government), Catholic and independent (private) schools; Exclusion: missing data | Exposure: Soft drinks consumed while watching TV; Comparator: Change in TV-related soft drink intake baseline to follow up (categorical; cups/d):; No change; Increase; Decrease; Assessment methods and timing:; Reported how often they consumed a soft drink (frequency, not amount); not validated; At baseline (2004-06), follow-up (200911); analyzed as change over time; Outcomes and assessment methods:; At baseline, height and weight measured (methods NR); At follow-up, height and weight selfreported; Healthy: BMI < 25 kg/m2; Overweight: BMI 25 kg–29.9 kg/m2; Obesity: BMI ≥30 kg/m2; At baseline (2004-06), follow-up (2009-11) | [underlined: Change in BMI] based on change in TVrelated soft drink consumption; ANOVA, Mean (SD); No change: 0.59 (2.32); Increase: 0.90 (2.54); Decrease: 0.60 (2.50); P=0.32 | Model adjustments:; - TEI: no; - Key confounders: anthropometry at baseline; - Other: N/A; Limitations:; - Did not account for key confounders: sex, age, race and/or ethnicity, socioeconomic position,physical activity, diet quality; - Exposure data limited to “TV viewing”, Exposure based on frequency of consumption, not amount , No info on noncompleters, Follow-up weight and height self-reported, No preregistered data analysis plan; Funding:; National Health and Medical Research Council, the National Heart Foundation, the Tasmanian Community Fund and Veolia Environmental Services; study sponsors: Sanitarium, ASICS and Target
Dhingra, 2007^128^; PCS, Framingham Offspring Study (offspring of the original Framingham Heart Study cohort), U.S.; Analytic N=3,321-4,277 (depending on outcome); Included in meta-analysis: yes; Study purpose: To test the hypothesis that greater soft drink consumption increases the risk of developing metabolic risk factors in middle-aged adults in the community; Participant characteristics at baseline: Adults; - Age: mean 52.9y; - Female: 57%; - Race/ethnicity: 100% White; - SEP: NR; - Anthropometry: Mean (SD); BMI: ~27.7 (5.1)kg/m2; Mean WC: ~36.9 (5.8)cm; - Physical activity: Physical activity index %, Mean (SD): 36 (7); - Smoking: Smokers ~20%; - Alcohol intake: NR; - Diet quality: NR; - TEI: Mean (SD): 1,941 (670); - Study beverage intake at baseline: Categorical, by 12oz svg/d:; <1: 65%; 1: 21%; ≥2: 14%; Inclusion: MetS at baseline 2 consecutive examinations from 4th to 7th examination cycles (1998-2001); Exclusion: missing data on covariates, prevalent cardiovascular disease | Exposure: “Soft drinks” (regular or diet), svg=12oz; Comparator: Categorical intake: <1 drink/d (REF), 1, ≥1, or ≥2 svg/d; Assessment methods and timing:; Physician-administered questionnaire (no info on validity); Baseline (examination 4), 4y, and 8y follow ups; analyzing intake and outcome over each 4y period; Outcomes and assessment methods: anthropometry measured during physical exam; Baseline, ~4 year follow up | [underlined: High WC at each 4y follow up period (≥102 cm men, ≥88 cm women):] OR (95% CI), fully adjusted model; None/<1 svg/d: REF; 1 svg/d 1.25 (1.02 to 1.54); ≥2 svg/d 1.40 (1.08 to 1.83); ≥1 svg/d 1.30 (1.09 to 1.56); [underlined: Obesity at each 4y follow up period (BMI ≥30)]: OR (95% CI), fully adjusted model; None referent; 1 serving/d 1.21 (0.90 to 1.62); ≥2 serving/d 1.50 (1.06 to 2.11); ≥1 serving/d 1.31 (1.02 to 1.68) | Model adjustments:; - TEI: yes; - Key confounders: sex, age, anthropometry at baseline, physical activity, smoking, diet quality (dietary intake of saturated fat, trans fat, fiber, and magnesium); - Other: Glycemic index; Limitations:; - Did not account for key confounders: race and/or ethnicity, socioeconomic position; - No information on non-completers; No preregistered data analysis plan; Funding:; NIH; American Diabetes Association
Drapeau, 2004^129^; PCS, Quebec Family Study, Canada; Analytic N=248; Included in meta-analysis: no; Study purpose: To verify whether changes in some dietary patterns over a 6-y follow-up period would be associated with weight changes; Participant characteristics at baseline: Parents and adult offspring; - Age: Mean (SEM): 39.6y (0.9), Range: 18-65y; - Female: 55%; - Race/ethnicity: NR; - SEP: NR; - Anthropometry: BMI, Mean (SEM): 25.3 (0.3), Range: 17.4-55.6; - Physical activity: NR; - Smoking: NR; - Alcohol intake: Macro- and micronutrient intakes reported in paper; - Diet quality: Macro- and micronutrient intakes reported in paper; - TEI: NR; - Study beverage intake at baseline: NR; Exclude: missing any dietary data; responding “I don’t know” to any dietary intake category | Exposure: Regular sodas (Pepsi, 7-Up, Coke, Sprite, etc); Fruit beverages (sugaradded beverage, cocktail juice); Comparator: Continuous intake; Assessment methods and timing: 3-d dietary record; Baseline, 6y; analyzed as change in intake over time; Outcomes and assessment methods: Weight, waist circumference, sum of 6 skinfold thicknesses (triceps, biceps, medial calf, subscapular, suprailiac, and abdominal) measured by study personnel Body fat percentage estimated using underwater weighing; Baseline, 6y | [underlined: Body fat percentage change over 6y] by change in intake, linear regression; Regular soda: NS, Data NR; Fruit beverages: NS, Data NR; [underlined: Waist circumference change over 6y] by change in intake, linear regression; Regular soda: NS, Data NR; Fruit beverages: NS, Data NR; [underlined: Sum of 6 skinfold thicknesses change][underlined: over 6y] by change in intake, linear regression; Regular soda: NS, Data NR; Fruit beverages: NS, Data NR; [underlined: Weight change over 6y] by change in intake, linear regression; Regular soda: NS, Data NR; Fruit beverages: NS, Data NR | Model adjustments:; - TEI: no; - Key confounders: age, anthropometry at baseline, physical activity; - Other: N/A; Limitations:; - Did not account for key confounders: sex, race/ethnicity, SEP, smoking, diet quality; - Did not account for all key confounders; Validation of 3day dietary record unclear; No information on non-completers; No preregistered data analysis plan; Funding:; Canadian Institutes of Health Research
Duffey, 2010^130^; PCS, Coronary Artery Risk Development in Young Adults (CARDIA) Study, U.S.; Analytic N=2,444; Included in meta-analysis: no; Study purpose: To examine the relation between consumption of low- and whole-fat milk, fruit juice, and SSB and cardiometabolic risk factors; Participant characteristics at baseline: adults; - Age: Mean (SD): 25.0 y (3.6); - Female: 54%; - Race/ethnicity: 53% White; 47% Black; - SEP: NR; - Anthropometry: Mean (SD); BMI: 24.5 (5.0) kg/m2; WC: 77.3 cm (10.9); - Physical activity: Mean (SD): 429 exercise units/wk (302); - Smoking: Current 28.1%, Former 13.1%, Never 58.7%; - Alcohol intake: NR; - Diet quality: NR; - TEI: NR; energy from food, Mean: 2347 kcal; - Study beverage intake at baseline: SSB at baseline: 95% consuming; Among consumers, Mean (SE), 188 (3) kcal/d; Included in original cohort: age between 18-30 at baseline; White or Black race; permanent residence in one of 4 recruitment sites (Birmingham, AL, Chicago, IL, Minneapolis, MN, Oakland, CA); free of a long-term disease or disability that would interfere substantially with any part of the examination (“Thus, persons who were blind, deaf, mute, mentally retarded, or unable to walk on a treadmill were excluded.”); Excluded from original cohort: pregnant or up to 3 months post-partum; Excluded from current analyses: people with a high WC at baseline or year 7 | Exposure: SSB (sugar-sweetened soda and fruit drinks); Comparator: Continuous (kcal/d); Categorical (quartiles); Assessment methods and timing:; Semi-quantitative, intervieweradministered, validated FFQ; Represents previous month; At baseline, 7y follow-up (averaged); Outcomes and assessment methods:; WC at minimum abdominal girth measured in duplicate; High WC defined as WC>88cm (women) or >102cm (men); Baseline, 20y follow-up | [underlined: High WC], Poisson regression, RR (95% CI); SSB intake, categorical: 1.09 (1.04, 1.15), P for trend <0.001; SSB intake, continuous: 1.06 (1.02, 1.10) P<0.05 | Model adjustments:; - TEI: yes; - Key confounders: sex, age, race and/or ethnicity, anthropometry at baseline, physical activity, diet quality, smoking; - Other: Calories from alcohol, CARDIA exam center; Limitations:; - Did not account for key confounders: socioeconomic position; - Unclear if exposure assessment tool is validated; High missing data; No preregistered data analysis plan; Funding:; Danone Research Center; NIH; UNC-CH Center for Environmental Health and Susceptibility; UNC-CH Clinic Nutrition Resarch Center; Carolina Population Center; University of Alabama at Birmingham Coordinating Center; University of Alabama at Birmingham Field Center, University of Minnesota Field Center, Northwestern University Field Center, Kaiser Foundation Research Institute
Ferreira-Pêgo, 2016^132^; PCS (secondary analysis of trial data), PREDIMED (PREvención con DIeta MEDiterránea), Spain; Analytic N=1,868; Included in meta-analysis: no; Study purpose: To evaluate the associations between intakes of SSB, artificially sweetened beverages, and natural and bottled fruit juices and the incidence of metabolic syndrome in elderly individuals at high risk of cardiovascular disease.; Participant characteristics at baseline: adults at high risk CVD; - Age: Mean (SD): 67y (6); - Female: 53%; - Race/ethnicity: NR; - SEP: NR; - Anthropometry: BMI Mean (SD): 28.3 (3.5) kg/m^2^; - Physical activity: Leisure time MET-min/d: ~274; - Smoking: Never 58%; Current 17%; Former 26%; - Alcohol intake: MET score by servings of SSB: <1/wk 9.0 ± 1.9, 1-5/wk 8.7 ± 1.9, >5/wk 7.8 ± 2.0; - Diet quality: MET score by servings of SSB: <1/wk 9.0 ± 1.9, 1-5/wk 8.7 ± 1.9, >5/wk 7.8 ± 2.0; - TEI: kcal/d, Mean (SD): 2322.6 (~530); - Study beverage intake at baseline: Mean SSBs: 14.5 mL/d; Bottled fruit juices: 16.6 mL/d; Inclusion: (men aged 55–80 y and women aged 60–80 y, no history of CVD at baseline but were at high cardiovascular risk because of the presence of T2D or ≥3 of the following risk factors: current smoking (>1 cigarette/d during the past month), hypertension (systolic blood pressure ≥140 mm Hg, diastolic blood pressure ≥90 mm Hg, or taking antihypertensive medication), high LDL cholesterol (≥160 mg/dL), low HDL cholesterol (<40 mg/dL for men or <50 mg/dL for women), BMI ≥25kg/m2, or family history of premature CVD; Exclusion: severe chronic illness, drug or alcohol addiction, history of allergy or intolerance to olive oil or nuts, and a low predicted likelihood of changing dietary habits according to Prochaska and DiClemente’s stages-of-change model | Exposure: Bottled fruit juices (natural fruit juice that has been chemically changed by using authorized methods and packed and commercialized for subsequent consumption (i.e., contains added sugars or not); (1svg=200mL); Comparator: SSBs, categorical <1 svg/wk (Ref), 1-5, >5; Assessment methods and timing:; Validated FFQ assessing habitual intake for previous year; Baseline, annually for ≥2y; averaged; Outcomes and assessment methods: Weight: measured by trained personnel with calibrated scales; Height: measured by trained personnel with a wall-mounted stadiometer.; Waist circumference measured using an anthropometric tape midway between the lower rib and the superior border of the iliac crest; Abdominal obesity: waist circumference ≥88cm in women and ≥102 cm in men Baseline, yearly during follow-up period of ≥2y | [underlined: Incidence abdominal obesity at 2y],; Multivariable time-dependent Cox proportional regression HR (95% CI); SSB average over time:; <1 serv/wk: Ref; 1-5 serv/wk: 1.13 (0.81, 1.57); >5 serv/wk: 1.20 (0.62, 2.30); P for trend: 0.42; Bottled fruit juice average over time:; <1 serv/wk: Ref; 1-5 serv/wk: 0.96 (0.72, 1.29); >5 serv/wk: 0.46 (0.21, 1.03); P for trend: 0.08 | Model adjustments:; - TEI: yes; - Key confounders: sex, age, anthropometry at baseline, physical activity, smoking, diet quality (fruits, vegetables, legumes, cereals, meat, fish, baker, dairy products, olive oil, nuts); - Other: Intervention group; alcohol; prevalence of MetS components at baseline; Limitations:; - Did not account for key confounders: Race and/or ethnicity, SEP; - No information on whether or not amount of missing data varied across exposure groups, Follow-up time differs among participants, No preregistered data analysis plan; Funding:; Spanish Ministry of Health, the Thematic Network, FEDER (European Regional Development Fund), the Centre Catalá de la Nutrició de l’Institut d’Estudis Catalans, and the Fundació ‘‘LaMarat´ o de TV3’’
Fowler, 2015^133^; PCS, San Antonio Longitudinal Study of Aging (SALSA), U.S.; Analytic N=466; Included in meta-analysis: no; Study purpose: To examine the relationship between diet soda intake and long-term waist circumference change; Participant characteristics at baseline: older adults (65+yo); - Age: ~69y; - Female: ~60%; - Race/ethnicity: ~50% European-American ; ~50% Mexican-American; - SEP: ~35% suburb residents; ~20% barrio residents; - Anthropometry: BMI ~29 kg/m2; WC ~100cm; ~78% overweight/obesity; - Physical activity: leisure time energy expenditure ~1800 kcal/wk; - Smoking: ~10%; - Alcohol intake: NR; - Diet quality: NR; - TEI: NR; - Study beverage intake at baseline: ~0.25/d; Inclusion: surviving SAHS participants aged 65+ at the time of the SALSA baseline (BL) examination (1992-1996); Exclusion: missing data | Exposure: Regular soda intake; Comparator: Regular soda intake, categorical; None/Non-users: 0-0.05 sodas/d; Occasional users: >0 but <1 soda/d; Daily users: ≥1 soda/d; Assessment methods and timing:; Questionnaire; represents weekly intake; non-validated; At baseline and beginning of each followup interval (~7y, 8.5, 10y from baseline); intake “status” reset at beginning of each interval; Outcomes and assessment methods: Height and weight measured; BMI calculated as kg/m2; Waist Circumference (WC) measured in cm at the level of the umbilicus; At baseline, 3 follow-ups: FU1 ~7y, FU2 ~1.5y; FU3 ~1.5y; total ~9.4y (range 4.512.5y) | [underlined: Change in WC, cm], over interval, By regular soda consumption category, Mean (95% CI); None/Non-User: 1.93 (1.44, 2.42) (ref); Occasional: 0.37 (−0.31, 1.05), P=0.001; Daily: 1.68 (0.36, 2.99); P-trend: NS | Model adjustments:; - TEI: no; - Key confounders: sex, age, race/ethnicity, socioeconomic position (education, neighborhood), anthropometry at baseline, physical activity, smoking; - Other: Diabetes, length of follow-up interval; Limitations:; - Did not account for key confounders: diet quality; - Exposure data collection tool not validated, No preregistered data analysis plan; Funding:; NIA;,NIDDK; NCRR; CTSA
Fowler, 2008^134^; PCS, San Antonio Heart Study, U.S.; Analytic N=3,371; Included in meta-analysis: no; Study purpose: To examine the relationship between artificially sweetened beverage consumption and long-term weight gain in the San Antonio Heart Study; Participant characteristics at baseline: Adults; - Age: Mean~44y (Range=25-64y); - Female: 58%; - Race/ethnicity: 36% Non-Hispanic White; 64% Mexican American; - SEP: Education: Mean~12y Socioeconomic index: Mean~51; - Anthropometry: Mean BMI: ~27 kg/m2 Overweight ~65%, Obesity ~25%; - Physical activity: Currently exercising ~27%; Exercise frequency, Mean~1.7x/wk; - Smoking: 26% current smokers; - Alcohol intake: NR; - Diet quality: NR; - TEI: Mean~1900 kcal/d; - Study beverage intake at baseline: SSB intake, Mean~2 drinks/d; Included: cohort of Mexican Americans and nonHispanic whites; age 25-64y at baseline; residing in San Antonio, TX; follow-up exam data 7-8y after baseline; baseline ASB dose, baseline and followup BMI, and all covariate data available | Exposure: SSB (regular sodas); Comparator: Categorical intake (None (ref); Q1: <3 drinks/wk; Q2: 3-10; Q3: 11-21; Q4: ≥22); Assessment methods and timing:; Participants reported soft drink use and were asked whether they usually drank regular sodas. Details NR.; At baseline; Outcomes and assessment methods: Standard anthropometric measurements were performed; Weight categories were defined as follows: normal wt, BMI<25 kg/m2; overweight, BMI ≥25 and <30 kg/m2; obesity, BMI ≥ 30 kg/m2; Incidence of overweight or obesity defined as % of normal wt participants who developed overweight or obesity by follow-up; Change in BMI calculated as BMI at follow-up minus BMI at baseline; At baseline, 7-8y follow-up | [underlined: Change in BMI (kg/m2)], Mean (SE); Non-SSB drinkers (ref): 1.48 (1.30, 1.66); Q1: 1.18 (0.90, 1.45); Q2: 1.17 (0.93, 1.41), P=0.04; Q3: 1.05 (0.83, 1.26), P=0.003; Q4: 1.15 (0.95, 1.34), P=0.02; P for trend=0.009; In sub-analyses excluding interim artificial sweetener adopters and discontinuers, the relationship between SSB consumption and change in BMI was NS. | Model adjustments:; - TEI: no; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position, anthropometry at baseline, physical activity (baseline and interim change), smoking (baseline and interim change); - Other: N/A; Limitations:; - Did not account for key confounders: diet quality; - Exposure assessment tool not validated; Exposure data only measured at baseline; No information on non-completers; No preregistered data analysis plan; Funding:; NIH; USDA
French, 2012^29^; PCS (secondary analysis of trial data), U.S.; Analytic N=225; Included in meta-analysis: no; Study purpose: To examine associations between television viewing, sugar-sweetened beverage consumption, eating out, physical activity, and body weight change over 1 year; Participant characteristics at baseline: Adults; - Age: ~41y; - Female: 61%; - Race/ethnicity: ~77% White; - SEP: ≥$100K 43%; - Anthropometry: BMI ~27.2 kg/m2; - Physical activity: Moderate/vigorous PA median scores: ~85; - Smoking: NR; - Alcohol intake: Fast food restaurants median times/wk : 0.5; - Diet quality: Fast food restaurants median times/wk : 0.5; - TEI: NR; - Study beverage intake at baseline: SSB, portions/wk; Adults: ~0.14; Inclusion: at least one adult and two HH members (including the adult) ages > 12 yrs; 2) residence in a private house or apartment within 20 miles of the university; 3) HH TV viewing weekly average of > 10 hrs per person; 4) no HH members with dietary, medical, psychological, or physical limitations that would prevent their participation in intervention activities; and 5) willingness to be randomized to active intervention or control group. All HH members were required to consent or assent prior to HH enrollment; Exclusion: NR | Exposure: fruit drinks, such as cranberry cocktail, Hi-C, lemonade, or Kool-Aid; regular (non-diet) soft drinks, soda, or pop; Comparator: Categorical: difference between intake at 12mo and baseline, portions/wk; (Decrease; No change/increase); Assessment methods and timing: Modified FFQ; intake over past month; validation not clear; At baseline and 12mo (after 12mo intervention); analyzed as change over time; Outcomes and assessment methods: Height and weight measured by trained research staff; BMI calculated for adults; BMI z-score calculated for adolescents; Weight measured using mechanical weight or beam-scale; Age- and sex-specific BMI z-scores (BMI z-score) calculated using Lambda-MuSigma method; Obesity (BMI>30 kg/m2) At baseline and 12mo | [underlined: Change in BMI] per SSB change over; 12mo, LSMean (SE); Adults (BMI); Decrease (n=78): 29.06 (0.18); No change/increase (n=68): 29.54 (0.19); P=0.09 | Model adjustments:; - TEI: no; - Key confounders: age, race/ethnicity, socioeconomic position (income and education), anthropometry at baseline, smoking in adults; - Other: treatment group; Limitations:; - Did not account for key confounders: physical activity, diet quality; - Attrition can’t be determined because baseline n NR, Bias due to missing data can’t be determined, Exposure data collection tool validation not clear, No preregistered data analysis plan; Funding:; NIH, NCIE
Funtikova, 2015^135^; PCS, Spain; Analytic N=2,112; Included in meta-analysis: yes; Study purpose: To assess the relation between consumption of nonalcoholic caloric beverages, including soft drinks, fruit juice, whole milk, and skim and low-fat milk, and changes in waist circumference and odds of 10-y incidence of abdominal obesity; Participant characteristics at baseline: Adults; - Age: Mean: ~49.2y; - Female: 53%; - Race/ethnicity: NR; - SEP: Higher education ~37%; - Anthropometry: Mean: WC, ~89.6 cm; - Physical activity: Mean: ~200 MET-min/d (leisure time); - Smoking: Current smoker ~26%; - Alcohol intake: validated, modified Mediterranean Diet Score (mMDS): ~17.3 (out of a possible 30); - Diet quality: validated, modified Mediterranean Diet Score (mMDS): ~17.3 (out of a possible 30); - TEI: Mean: ~11.2 MJ/d kcal/d; - Study beverage intake at baseline: Soft drinks, mL/d, Mean (SD): 42 (109); no consumption: 57%, <1 svg/d: 35%, ≥1 svg/d: 8%; Included in original cohort (n=3058): adults aged 25-75y residing in Girona, Spain; Excluded from current analyses: no longer residing in catchment area (n=343); lost to followup (n=534), missing data for WC (n=37) and smoking status (n=32) | Exposure: Soft drinks (including carbonated sugar-sweetened beverages) (1 svg = 200mL); Comparator: Soft drink intake (continuous; 100 kcal/d); Soft drink intake (categorical; svg/d): No consumption (ref), <1, ≥1; Soft drink intake (categorical; change in consumption): No consumption (ref), Decrease, Increase, Maintain; Assessment methods and timing:; Validated, 166-item FFQ administered by trained interviewer; Represents intake during previous year; Baseline, 9y follow-up; Outcomes and assessment methods: WC measured midway between lowest rib and iliac crest with participant lying horizontally. Abdominal obesity defined as >102 cm for men and >88 cm for women; Baseline, 9y follow-up | Soft drinks, continuous; WC, cm, Change per 100 kcal/d increase, Mean (95% CI), linear regression; 1.10 (0.18, 2.03), P=0.018; Men: 0.97 (−0.14, 2.08), P=0.09; Women: 1.32 (−0.23, 2.86), P=0.10; Soft drinks, categorical; Abdominal obesity, OR (95% CI), logistic regression; Incidence by baseline intake:; No consumption (ref); <1 svg/d: 1.22 (0.90, 1.66); ≥1 svg/d: 1.77 (1.07, 2.93); Men (n=756); No consumption (ref); <1 svg/d: 1.03 (0.63, 1.69); ≥1 svg/d: 1.62 (0.83, 3.14); P trend=0.31; Women (n=723); No consumption (ref); <1 svg/d: 1.39 (0.94, 2.05); ≥1 svg/d: 1.64 (0.74, 3.64); P trend=0.07; Soft drinks (change in consumption), categorical; WC, cm, Change by change in consumption, Mean (95% CI), linear regression:; No consumption (ref); Decrease: 0.49 (−0.61, 1.58), P=0.38; Increase: 1.50 (0.36, 2.64), P=0.01; Maintain: 1.22 (0.13, 2.31), P=0.029; Men (n=1000); No consumption (ref); Decrease: 0.90 (−0.58, 2.37), P=0.23; Increase: 1.52 (0.01, 3.02), P=0.049; Maintain: 0.03 (−1.41, 1.46), P=0.97; Women (n=1112); No consumption (ref); Decrease: 0.17 (−1.42, 1.76), P=0.83; Increase: 1.49 (−0.21, 3.18), P=0.09; Maintain: 2.44 (0.81, 4.06), P=0.003 | Model adjustments:; - TEI: yes; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position, anthropometry at baseline, physical activity, diet quality (Mediterranean diet score), smoking; - Other: energy under- or over-reporting; Limitations:; - Did not account for key confounders: race and/or ethnicity; - Start of follow-up and exposure do not coincide; High attrition (31%) with no information on non-completers; No preregistered data analysis plan; Funding:; Catalan Government; Carlos III Health Institute European Fund for Regional Development; Catalonian Agency for the Administration of University and Research Grants
Garduño-Alanís, 2020^136^; PCS, Health, Alcohol, and Psychosocial factors in; Eastern Europe (HAPIEE); Russian cohort , Russia; Analytic N=5,205; Included in meta-analysis: no; Study purpose: To assess the longitudinal relationship between fruit juice, soft drink consumption and BMI in Eastern European cohorts; Participant characteristics at baseline: Adults; - Age: <55y: 36%; 55-65y: 40%; >65y: 23%; - Female: 55%; - Race/ethnicity: NR; - SEP: Education:; Primary or less- 11%, Vocational- 27%, Secondary 34%, University degree 29%; Marital status: living with a partner - 72%; - Anthropometry: Mean (SD) BMI 28.5 (5.5) kg/m2; - Physical activity: MET-h/day: %of sample <5: 29%, 5-15: 57%, >15: 15%; - Smoking: Never 58%; Former 14%; Regular 28%; - Alcohol intake: Fruit and vegetable consumption g/day: %of sample: <300 - 38%, 300-600 - 45%, >600 - 17%; - Diet quality: Fruit and vegetable consumption g/day: %of sample: <300 - 38%, 300-600 - 45%, >600 - 17%; - TEI: Kcal/day: <2000 - 55.8%, 2000-2500 - 24.3%, >2500 - 19.9%; - Study beverage intake at baseline: SSB consumption: Never drink 77.5%, <1/day 20.6%, >1/day 1.9%; Excluded: missing data (exposure, outcome, and covariates), extreme values for weight (>200kg), height (>205 cm) and energy intake (>5000 kcal or <500kcal/day) | Exposure: Non-alcoholic carbonated (fizzy) drinks, such as coke, fizzy orange or lemonade, one drink equivalent to 200 ml; & (separate exposure); Fruit juices such as apple drinks, one drink equivalent to 200 ml; Comparator: Drinkers versus nondrinkers; Assessment methods and timing: FFQ-country specfic items and portion sizes, foods, and drinks. Frequency in the last three months and answers converted to daily consumption.; Baseline (2002-2005); Outcomes and assessment methods: Height and weight measured in clinic by professional; missing data was replaced by self-reported measures (n=3085 at baseline); BMI calculated by body weight (kg)/ square of height (m); obesity defined as BMI>30 kg/m2 ; change in BMI was calculated by subtracting BMI at baseline from BMI at follow up; Baseline (2002-2005) and follow up (2006-2008) | [underlined: Unit change in BMI]: OR (95% CI), pvalue, multivariable logistic regression; Nondrinkers = REF; SSB drinkers 1.26 (1.09-1.45), P=0.001; [underlined: Unit change in BMI]: OR (95% CI), pvalue, multivariable logistic regression; Nondrinkers = REF; Fruit juice drinkers drinkers 0.92 (0.811.05), P=0.203 | Model adjustments:; - TEI: yes; - Key confounders: sex, age, socioeconomic position, anthropometry at baseline, physical activity, diet quality (F&V intake), smoking; - Other: Alcohol consumption, hx of disease (CVD, Diabetes, Cancer); Limitations:; - Did not account for key confounders: race and/or ethnicity; - Exposure not well defined ; Exposure data only measured at baseline; Very low intake of target beverage (SSB); No information on non-completers; weight and height was/were self-reported (for missing baseline values); No preregistered data analysis plan; Funding:; Wellcome Trust, the US National Institute of Aging, and the MacArthur Foundation Initiative on Social Upheaval and Health
Gearon , 2018^137^; PCS, Melbourne Collaborative Cohort Study (MCCS), Australia; Analytic N=7,894; Included in meta-analysis: no; Study purpose: To quantify the mediating role of leisure time physical activity and five dietary behaviours on educational differences in 13-year BMI gain across adulthood; Participant characteristics at baseline: Adults; - Age: ~46y (Range 27-80y, focused on 40-69y); - Female: 61%; - Race/ethnicity: NR; - SEP: NR; - Anthropometry: BMI Women ~25, Men ~26; - Physical activity: leisure time score ~4; - Smoking: Never smoker, Women ~62%, Men ~52%; - Alcohol intake: Nutrient rich foods/wk mean (IQR): stratified by sex and education in paper; Exclusion: didn’t attend follow up, southern European country of birth, aged > 65 years at follow-up, cancer or cardio-metabolic diseases or conditions at baseline lost weight over time, extreme energy intakes (i.e., in the 1st or 99th percentile of energy intake), missing information on variables of interest | Exposure: Soft drink; Comparator: Categorical intake (<1/wk, ≥1/wk); Assessment methods and timing:; FFQ designed for the study; based on frequency, not amount; not validated At baseline; Outcomes and assessment methods: Weight and WC measured by practitioner; Height measured by practitioner at baseline only; At baseline and 13y follow-up | [underlined: BMI change over 13y], Soft drink <1/wk versus ≥ 1/wk, Linear regression, β (95% CI); Women: 0.01 (−0.14, 0.16); Men: −0.02 (−0.14, 0.10) | Model adjustments:; - TEI: no; - Key confounders: sex, age, smoking; - Other: alcohol; Limitations:; - Did not account for key confounders: race and/or ethnicity, socioeconomic position, anthropometry at baseline, physical activity, diet quality,; - Bias due to missing data can’t be determined, Exposure data only measured at baseline, Exposure classified by frequency not amount, Exposure data collection tool not validated, No preregistered data analysis plan; Funding:; NHLBI; NCI
Gibbs, 2020^138^; PCS (secondary analysis of trial data), Secondary analysis of the MAINTAIN-pc weight loss trial , U.S.; Analytic N=194; Included in meta-analysis: yes; Study purpose: To identify dietary and physical activity habits associated with 6- and 24-month weight regain among participants in a weight loss maintenance clinical trial; Participant characteristics at baseline: Adults; - Age: mean (SD) 53.4 (12.2)y; - Female: 74%; - Race/ethnicity: 88% White; 10% Black; 2% Asian; - SEP: 5% high school education; 19% some college; 32% college; 44% graduate degree; - Anthropometry: BMI: 30.4 (5.9) kg/m2; - Physical activity: 45.89 (40.06) min/d of MVPA; - Smoking: NR; - Alcohol intake: 5.13 (2.85) svg/d of fruits and vegetables; - Diet quality: 5.13 (2.85) svg/d of fruits and vegetables; - TEI: NR; - Study beverage intake at baseline: 0.46 (1.09) svg/wk of sugary beverages; Inclusion: participant in MAINTAIN-pc trial with available follow up data, 18-75y, BMI ≥25 kg/m2, intentional weight loss of ≥5% in the previous 2y, access to Internet-connected computer; Exclusion: medical explanation for recent weight loss (e.g., cancer), active preparation for bariatric surgery, bariatric surgery in the previous 5 years, or pregnancy | Exposure: Sugary beverages (12oz svg); Comparator: Continuous intake (12oz/wk); Assessment methods and timing:; Validated diet habit survey; Baseline, 6mo and 24mo follow-up; analyzed as change over time; Outcomes and assessment methods: Weight was measured by study staff; Baseline, 6mo and 24mo follow-up | [underlined: Change in weight (kg)] by 1-unit change in SSB intake (12 oz/wk): β (95% CI) Adjusted for age, gender, randomized group, and stratum; 6mo: 0.25 (−0.52, 1.02), p=0.5235; 24mo: 1.96 (0.86, 3.06), p=0.0006; Additionally adjusted for dietary habits and physical activity; 24mo: 1.50 (0.51, 2.48), p=0.003 | Model adjustments:; - TEI: no; - Key confounders: sex, age, anthropometry at baseline, physical activity, diet quality (weekly intake of restaurant foods, fish, desserts, low-fat foods); - Other: randomized group; primary care practice stratum; sedentary behavior; Limitations:; - Did not account for key confounders: smoking, race and/or ethnicity, socioeconomic position, diet quality; - No preregistered data analysis plan; Funding:; AHRQ; NIH
Gonzalez-Morales, 2020^139^; PCS, Health Workers Cohort Study, Mexico; Analytic N=1,268; Included in meta-analysis: yes; Study purpose: To estimate the association between soft drink intake and body weight, and explored if this association differed by levels of leisure-time physical activity; Participant characteristics at baseline: adults; - Age: mean (SD) 45.3 (12.7)y, range 19-82y; - Female: 74%; - Race/ethnicity: NR; - SEP: 12% elementary school; 37% secondary or high school; 50% college or higher; - Anthropometry: BMI: 26.5 (4.3) kg/m2; - Physical activity: Leisure time physical activity, min/d, Mean (SD): 24.1 (29.2); Low PA (<21.4min/d): 61%; High PA (≥21.4min/d): 39%; - Smoking: 58% never, 25% past, 17% current; - Alcohol intake: 4.0 (4.3) svg/d of fruit; 4.3 (3.0) svg/d of vegetables; - Diet quality: 4.0 (4.3) svg/d of fruit; 4.3 (3.0) svg/d of vegetables; - TEI: NR; - Study beverage intake at baseline: 0.5 (0.7) svg/d of soft drink; Inclusion: adults health care workers (participating locations); Exclusion: <19y; missing weight, soft drink intake, leisure-time physical activity, or covariates; pregnant women; energy intake <600 or > 6000 kcal/d | Exposure: Soft drink (cola and flavored sodas, not including diet sodas); 1 svg = 355 mL; Comparator: Continuous intake (svg/d); Assessment methods and timing:; Validated semi-quantitative FFQ assessing usual intake over the previous year; Baseline (2004-2006), 6y follow-up (2010- 2012); analyzed as change over time; Outcomes and assessment methods: Weight was measured by trained personnel; Baseline (2004-2006), 6y (2010-2012) | [underlined: Change in weight (kg)] by change in soft drink intake (svg/d), β (95% CI); Over 6y follow-up; All: 0.02 (−0.84, 0.79); BMI <25 kg/m2: 0.47 (−0.49, 1.43); BMI ≥25 kg/m2: −0.31 (−1.09, 0.47); Per year; All: 0.11 (−0.02, 0.23); BMI <25 kg/m2: 0.08 (0.08, 0.24); BMI ≥25 kg/m2: 0.10 (−0.04, 0.24) | Model adjustments:; - TEI: no; - Key confounders: sex, age, socioeconomic position, anthropometry at baseline, physical activity, diet quality (fruits, vegetables, red meat, total dairy, nuts, yogurt, white bread, tortillas, and orange juice), smoking; - Other: time interactions with SSB intake, physical activity, sex, and age; screen time; sleep; alcohol intake; chronic disease; Limitations:; - Did not account for key confounders: race and/or ethnicity; - High attrition; No preregistered data analysis plan; Funding:; Bloomberg Philanthropies; NIH
Halkjaer, 2009^140^; PCS, Danish Diet, Cancer, and Health study, Denmark; Analytic N=42,696; Included in meta-analysis: yes; Study purpose: To investigate the association between intake from 21 food and beverage groups and the subsequent 5-year difference in waist circumference; Participant characteristics at baseline: adults; - Age: 56y (Range: 50-64y); - Female: 53%; - Race/ethnicity: NR; - SEP: NR; - Anthropometry: BMI Mean: 25 kg/m2; - Physical activity: Perform ≥30min sport/wk; - Smoking: Current: 33%; - Alcohol intake: Median (5th-95th %), kcal/d; Vegetables: Male(M): 67 (22-146); Female(F): 74 (24-169); Fruits: M: 84 (16-277); F: 114 (25-320); Soft drinks: M: 6.8 (0.1-81); F: 2.0 (0.1-35); - Diet quality: Median (5th-95th %), kcal/d; Vegetables: Male(M): 67 (22-146); Female(F): 74 (24-169); Fruits: M: 84 (16-277); F: 114 (25-320); Soft drinks: M: 6.8 (0.1-81); F: 2.0 (0.1-35); - TEI: NR; - Study beverage intake at baseline: Soft drink: Median~5 kcal/d; Include: Age 5-64y, born in Denmark, no hx of cancer; Exclude: too many data errors, missing data on follow-up time | Exposure: Soft drinks (sugar-sweetened soft drinks); Comparator: Continuous intake (per 60 kcal/d increments); Assessment methods and timing:; Validated FFQ; represents usual intake Baseline; Outcomes and assessment methods:; - Height, weight, waist circumference, hip circumference measured at baseline; - Follow-up weight and WC were selfreport; - Waist circumference measured at the smallest horizontal circumference between the ribs and iliac crest (the natural waist), or, in case of an indeterminable waist narrowing, halfway between the lower rib and the iliac crest; SELF-REPORTED: measuring tape was provided, participants were told to measure WC at the level of the umbilicus; - Hip circumference was measured at the largest horizontal expansion of the buttocks; Baseline, 5y follow up | [underlined: Waist circumference, cm], 5yr change per 60 kcal/d soft drink, Linear regression, β (95% CI); Women: 0.01 (−0.24, 0.27); Men: −0.02 (−0.12, 0.08); Interaction, P=0.80 | Model adjustments:; - TEI: yes; - Key confounders: Sex, age, anthropometry at baseline, physical activity, smoking; - Other: Alcohol; Limitations:; - Did not account for key confounders: Race and/or ethnicity, SEP, diet quality; - Attrition 25% without information on non-completers, Exposure data only measured at baseline, WC self-reported, No preregistered data analysis plan; no reporting of other outcomes measured (weight, BMI, hip circumference); Funding:; National Danish Research Foundation; Diet, Obesity and Genes project, supported by European Community
Hasselbalch, 2010^141^; PCS, GEMINAKAR sample within Danish Twin Registry, Denmark; Analytic N=238 twin pairs (for weight change); 192 twin pairs for WC change; Included in meta-analysis: no; Study purpose: To determine whether habitual dietary intake was associated with body fat mass and body fat distribution, independently of possible confounding by the genetic and shared environmental background; Participant characteristics at baseline: Adult Danish twins; - Age: Mean: 38y (range: 18-67y); All information on key confounders is based on the cross-sectional sample, of which the longitudinal sample is a smaller subset; - Female: 51%; - Race/ethnicity: NR; - SEP: NR; - Anthropometry: Baseline BMI: 25.1±3.0 (males); 23.8±3.9 (females); Baseline waist circumference: 90.0±8.6 cm (males); 78.1±10.1 cm (females); - Physical activity: NR; - Smoking: NR; - Alcohol intake: Baseline dietary energy density: 3.5±0.8 kJ/g (males); 2.9±0.9 kJ/g (females); - Diet quality: Baseline dietary energy density: 3.5±0.8 kJ/g (males); 2.9±0.9 kJ/g (females); - TEI: Males: 11.2±3.4 MJ Females: 8.6±2.2 MJ; - Study beverage intake at baseline: Baseline energy from soft drinks: 179.8±284.8 kJ (males); 127.4±319.9 kJ (females); Excluded: Dizygotic twin pairs; individuals or pairs with diabetes or CVD, pregnancy, breastfeeding, alcohol/drug abuse or conditions making it difficult to participate in clinical exam | Exposure: Sugar-sweetened soft drinks; Comparator: Different intake of SSB (continuous); Assessment methods and timing:; Validated semi-quantitative FFQ; At baseline (between 1997-2000); Outcomes and assessment methods: Weight and waist circumference measured by study staff at baseline, selfreported in 2002; Baseline (1997-2000) and 2002 | [underlined: Change in waist circumference], correlation coefficient; Women: Data NR; Men: NS; [underlined: Change in BMI], correlation coefficient; Women: Data NR; Men: NS; [underlined: Change in weight], correlation coefficient; Women: Data NR; Men: NS | Model adjustments:; - TEI: yes; - Key confounders: race/ethnicity, sex, age (comparison between MZ twins); physical activity; smoking; anthropometry at baseline; - Other: N/A; Limitations:; - Did not account for key confounders: socioeconomic position, diet quality; - Exposure data only measured at baseline; Weight and waist circumference were selfreported; No preregistered data analysis plan; Funding:; Danish Council for Strategic Research; Danish Medical Research Fund; Danish Diabetes Association; NOVO Foundation; Danish Heart Foundation; Apotekerfonden; European Union Contract; DIOGENES (supported by European Community)
Hosseinpour-Niazi, 2021^144^; PCS, Tehran Lipid and Glucose Study, Iran; Analytic N=1,915; Included in meta-analysis: no; Study purpose: To determine the prospective relationship between the consumption of SSB and 100% fruit juice and metabolic syndrome; Participant characteristics at baseline: Adults; - Age: Mean (SD): 36.5 (13.3)y; - Female: 60%; - Race/ethnicity: NR; - SEP: Baseline characteristics reported across tertiles (T1 and T3) of SSB intake % with academic degrees: T1: 25.7%, T3: 27.1%, p=0.694; Occupational status, % unemployed: T1: 65.7%, T3: 46.2%, p<0.001; - Anthropometry: BMI, mean (SD): 25.6 (4.5) kg/m2; - Physical activity: MET-h/week, mean (SD): T1: 4.6 (0.3), T3: 5.5 (0.3), p=0.061; - Smoking: % smoker at baseline: T1: 12.4%, T3: 33.1%, p<0.001; - Alcohol intake: NR; - Diet quality: NR; - TEI: Kcal/day, mean (SD); T1: 2147 (35); T3: 2570 (35); p<0.001; - Study beverage intake at baseline: Mean (SD): 33.5 (1.27) g/day; Median intake, g/day: T1: 3.4, T3: 56.4; Included: age ≥3y at baseline, resident of district 13 in Tehran; Excluded: refusal to complete FFQ (n=838), incomplete FFQ information (n=197), metabolic syndrome at baseline (n=879), pregnant or lactating at baseline or follow-up (n=28), daily energy intake < 500 and >4200 kcal/d (n=115), on a specific diet for hyperlipidemia, hypertension, or hyperglycemia (n=26), missing laboratory or anthropometric data related to metabolic syndrome diagnosis during follow-up (n=309) | Exposure: sugar sweetened carbonated soft drinks and sugar sweetened synthetic fruit juice that is not 100% juice; Comparator: Categorical (tertiles); Assessment methods and timing:; Validated semi-quantitative FFQ; represents intake over previous year.; Standard units or portion sizes were converted to grams.; 2006-2008 (baseline), 2008-2011, 20122015, 2016-2018; repeat assessments analyzed in same model, technique unclear; Outcomes and assessment methods: Height and weight: valid measure by study staff. BMI calculated from weight and height.; % weight change calculated by subtracting baseline weight from follow-up weight, divided by baseline weight, and multiplied by 100. Participants categorized as those who lost weight (≥-2%), those with weight stability (−1.9%–1.9%), and those who gained weight (≥2%).; 2006-2008, 2016-2018 (median follow-up: 8.91y (IQR: 7.98-9.69y)) | [underlined: Risk of weight gain ≥2%], multivariable Cox regression, HR (95% CI); T1: ref; T2: 1.04 (0.88, 1.21); T3: 1.08 (0.91, 1.27); p=0.667 | Model adjustments:; - TEI: yes; - Key confounders: sex, age, socioeconomic position (education levels, occupation status), anthropometry at baseline, physical activity, smoking; - Other: Family history of diabetes, anti-hyperglycemic medication use, antihyperlipidemic medication use, dietary cholesterol, fiber intake; Limitations:; - Did not account for key confounders: race and/or ethnicity, diet quality; - Start of follow-up and exposure do not coincide; High amount of missing data; No preregistered data analysis plan; Funding:; Research Institute for Endocrine Sciences, Shahid Beheshti University of Medical Sciences, Tehran, Iran
Inoue , 2010^145^; PCS, MY Health Up Study, Japan; Analytic N=24,596; Included in meta-analysis: no; Study purpose: To investigate the effect of weight perception and lifestyle on BMI over a 2-year period; Participant characteristics at baseline: Adults; - Age: Men 41 (9.9)y; Women 46 (10.0)y; - Female: 76%; - Race/ethnicity: NR; - SEP: All were employees at a large financial firm; - Anthropometry: Men 23.9 (3.2) kg/m2, Women, 22.5 (3.7) kg/m2; - Physical activity: NR; - Smoking: NR; - Alcohol intake: NR; - Diet quality: NR; - TEI: NR; - Study beverage intake at baseline: NR; Inclusion: employees of a Japanese financial firm; Exclusion: incomplete participation, missing data regarding age, gender, height, weight or weight perception, men over 70 years of age, males sales staff, pregnant | Exposure: Soft drinks, such as soda and juice; Comparator: Dichotomous intake (Almost everyday versus not); Assessment methods and timing:; Self-administered questionnaire (no further details given); Baseline (2004); Outcomes and assessment methods: Height and weight were measured during annual health check-up and used to calculate BMI.; Baseline, 2y follow-up | [underlined: Change in BMI (kg/m2) over 2y], Multiple regression, β (SE); Men; Do not drink SSB almost every day: REF Drink SSB almost every day: data NR, p=NS; Women; Do not drink SSB almost every day: REF; Drink SSB almost every day: 0.0083 (0.0235), p=0.0002 | Model adjustments:; - TEI: no; - Key confounders: sex, age, anthropometry at baseline, physical activity, smoking; - Other: weight perception, lifestyle factors (sleep, commute time, days off from work, hobby, lunch time, consumption of sweets, colleagues’ smoking, drinking); Limitations:; - Did not account for key confounders: race and/or ethnicity, socioeconomic position, diet quality; - Exposure not well defined; Exposure assessment tool not validated; Exposure data only measured at baseline; No information on non-completers; No preregistered data analysis plan; Funding:; None declared
Kaikkonen, 2015^146^; PCS, Young Finns Study, Finland; Analytic N=1,715; Included in meta-analysis: yes; Study purpose: To examine factors associated with weight change and obesity risk in young and middle-aged adults; Participant characteristics at baseline: Adults; - Age: Mean ~31.7y; - Female: 54%; - Race/ethnicity: NR; - SEP: Educational status (1=low to 3=high), Mean ~2.11; Occupational status (1=low to 3=high), Mean~1.9; - Anthropometry: Mean (SD): BMI (women), 24.38 (0.149); BMI (men), 25.64 (0.138); - Physical activity: Leisure-time physical activity (5=low to 15=high), Mean ~9.9; - Smoking: 23% smoker; - Alcohol intake: Monthly use (portions), mean (SE); Vegetables and fruits: Women: 39.8 (0.53); Men: 32.5 (0.57); Sweets and chocolate: Women: 9.71 (0.25); Men: 8.45 (0.26); Frequency to add salt to food (1=never, 3=always):; Women: 1.22 (0.01); Men: 1.28 (0.02); - Diet quality: Monthly use (portions), mean (SE); Vegetables and fruits: Women: 39.8 (0.53); Men: 32.5 (0.57); Sweets and chocolate: Women: 9.71 (0.25); Men: 8.45 (0.26); Frequency to add salt to food (1=never, 3=always):; Women: 1.22 (0.01); Men: 1.28 (0.02); - TEI: NR; - Study beverage intake at baseline:; Portions/month, Mean (SD): Women: 5.07 (0.23); Men: 8.43 (0.29); Included: participation in Young Finns Study examination beginning in 1980, outcome data at baseline (2001 in this study) and at follow-up (2007); Excluded: women who were pregnant in either 2001 or 2007 or had missing pregnancy information in 2001; weight loss >50kg | Exposure: Sugar-sweetened soft drinks; Comparator: Sugar-sweetened soft drink intake (continuous; portions/mo); Assessment methods and timing: Non-quantitative dietary use frequency questionnaire; Represents habitual intake; Baseline (2001; age 24-39y, mean ~32.7y); Outcomes and assessment methods: Height and weight measured by study personnel. Obesity defined as BMI ≥30; Baseline, 6y follow-up | [underlined: Change in weight (kg) over 6y] follow up, linear regression; Women (n=923): Not retained in final model; Data NR, P=NS; Women 24-27y (n=265): Beta=0.147, P=0.013; Women 30-39y (n=658): Not retained in final model; Data NR, P=NS; Women with weight gain >2kg (n=490): Not retained in final model; Data NR, P=NS; Men (n=792): Not retained in final model;; Data NR, P=NS; Men 24-27y (n=226): Not retained in final model; Data NR, P=NS; Men 30-39y (n=566): Not retained in final model; Data NR, P=NS; Men with weight gain >2kg (n=455): Not retained in final model; Data NR, P=NS; [underlined: Incident obesity], OR (95% CI), logistic regression Women (n=823): Not retained in final model; Data NR, P=NS Men (n=689): Not retained in final model;; Data NR, P=NS | Model adjustments:; - TEI: no; - Key confounders: sex, age, socioeconomic position, anthropometry at baseline, physical activity, smoking; - Other: Varied by sex and age group but in general included hormones and inflammatory markers, dietary habits and alcohol use, genetic factors, psychological factors, living habits and environment, childhood factors; Limitations:; - Did not account for key confounders: race and/or ethnicity, diet quality; - Exposure assessment tool not validated; Exposure data only measured at baseline; High attrition (25%) with no information on non-completers; No preregistered data analysis plan;; Funding:; Academy of Finland; Social Insurance Institution of Finland; Kuopio, Tampere and Turku University Hospital Medical Funds; Yrjo Jahnsson Foundation; Juho Vainio Foundation; Paavo Nurmi Foundation; Finnish Foundation of Cardiovascular Research; Finnish Cultural Foundation; Sigrid Juselius Foundation; Tampere Tuberculosis Foundation; Emil Aaltonen Foundation; Signe and Ane Gyllenberg Foundation; Bothnia Welfare Coalition for Research and Knowledge
Kang, 2017^147^; PCS, Korean Genome and Epidemiology Study (KoGES), Korea; Analytic N=5,797; Included in meta-analysis: no; Study purpose: To explore the sex-specific association between soft drink consumption and incident risk of metabolic syndrome in Korean adults during 10 years of follow-up; Participant characteristics at baseline: adults; - Age: ~51y; - Female: 48%; - Race/ethnicity: 100% Asian; - SEP: 27% Elementary school (≤6y); 57% Middle/high school (7-12y); 15% College or higher (>12y); - Anthropometry: BMI ~24 kg/m2; - Physical activity: ~23.6 MET/d; - Smoking: 56% Non-smokers, 27% Current, 16% Former; - Alcohol intake: NR; - Diet quality: NR; - TEI: ~1972 kcal/d; - Study beverage intake at baseline: 43% rarely/never, 38% <1/wk, 17% ≥1/wk-<4/wk, 3% ≥4 svg/wk; Inclusion: without MetS at baseline; Exclusion: refused to participate in follow-up examinations (n 747), those who provided insufficient information (n 313), those who did not respond to dietary examination (n 59) and those who had CVD or cancer (n 137) | Exposure: Soft drink (carbonated beverages, e.g., Cola and Sprite; did not examine consumption of diet soft drinks); Comparator: Soft drink intake (categorical):; Rarely/never; <1 svg/wk; ≥1 svg/wk to <4 svg/wk; ≥4 svg/wk; Assessment methods and timing:; Validated FFQ administered by trained dietitians; represents frequency and portion size of soft drink consumption during the past year; At baseline (2001-2002), and second follow-up (2005-2006); analysis of repeat measurements unclear; Outcomes and assessment methods: Height and weight measured with no shoes and while wearing light clothing by trained professionals; Waist circumference (WC) measured three times then averaged after measuring to the nearest 0.1 cm at narrowest point between lowest rib and the right iliac crest; Abdominal obesity defined based on MetS criteria from National Cholesterol; Education Program Adult Treatment Panel III (WC≥90cm for men or ≥80cm for women); At baseline (2001-2002), and every 2 years over a 10-yr period (Mean 5.7y) | [underlined: Incidence of Abdominal Obesity], Change according to soft drink consumption, Cox proportional hazard, HR (95% CI); [underlined: Total Sample]; Rarely/never (ref) versus.; <1/wk: 0.91 (0.81, 1.02); ≥1/week to <4/week: 1.11 (0.96, 1.29); ≥4/week: 1.17 (0.86, 1.60); P for trend 0.3434; P for interaction: 0.5079; [underlined: Men]; Rarely/never (ref) versus.; <1/wk: 0.87 (0.73, 1.03); ≥1/week to <4/week: 1.07 (0.87, 1.31); ≥4/week: 1.11 (0.74, 1.65); P for trend 0.6012; [underlined: Women]; Rarely/never (ref) versus.; <1/wk: 0.95 (0.81, 1.11); ≥1/week to <4/week: 1.12 (0.88, 1.43); ≥4/week: 1.32 (0.78, 2.23); P for trend 0.4387; Results were similar in analysis according to area of residence (rural versus. urban). | Model adjustments:; - TEI: yes; - Key confounders: sex, age, race/ethnicity socioeconomic position, anthropometry at baseline, physical activity, smoking; - Other: fiber, alcohol; Limitations:; - Did not account for key confounders: diet quality; - Attrition 18% without information on non-completers, Start of follow-up differed among participants, Not generalizable to other racial/ethnic groups, No preregistered data analysis plan; Funding:; Basic Science Research Program of the National Research Foundation of Korea funded by the Ministry of Education, Science and Technology
Kärkkäinen, 2018^148^; PCS, FinnTwin16, Finland; Analytic N=3,490; Included in meta-analysis: no; Study purpose: To assess factors associated with successful weight maintenance over ten years in a prospective general population sample of young adults; Participant characteristics at baseline: young adults; - Age: ~24y; - Female: 52%; - Race/ethnicity: NR; - SEP: 57% High school education; - Anthropometry: 18% Overweight, 4% Obesity; - Physical activity: ~5.0 MET; - Smoking: ~28%; - Alcohol intake: healthy foods mean:; women: ~2.9; men: ~2.5; High fat foods mean:; women ~2.0; men ~2.2; - Diet quality: healthy foods mean:; women: ~2.9; men: ~2.5; High fat foods mean:; women ~2.0; men ~2.2; - TEI: NR; - Study beverage intake at baseline: NR; Exclusion: chronic, potentially weight-affecting illnesses at mean age 24 or 34 (n = 285), | Exposure: Sweet drinks (sugared soft drinks or juices); Comparator: Sweet drink intake (continuous); Assessment methods and timing: Modified FFQ; represents frequency of consumption; At baseline; Outcomes and assessment methods: Height and weight were self-reported; BMI calculated as kg/m2; Waist circumference was self-reported: participants were sent a tape measure along with illustrated instructions; BMI & waist circumference were validated in a measured sub-sample; Weight status based on standard WHO definitions: Underweight (BMI < 19.5 kg/m2), Normal weight (BMI 19.5-24.9 kg/m2), Overweight (BMI 25-29.9 kg/m2), and Obesity (BMI >29.9 kg/m2); Weight maintenance defined as weight maintained within ±5% of baseline BMI At baseline (Wave 4, age ~24y), 10y follow-up (Wave 5, age ~34y) | [underlined: Weight maintenance versus weight gain][underlined: over 10 years], Logistic regression, OR (95% CI); Women: 0.79 (0.67, 0.93); Men: 1.14 (0.97, 1.34) | Model adjustments:; - TEI: no; - Key confounders: sex, socioeconomic position, anthropometry at baseline, physical activity, smoking; - Other: alcohol; Limitations:; - Did not account for key confounders: age, race and/or ethnicity, diet quality; - Missing data: participants who were excluded were more educated and less likely to smoke, Validity of FFQ unclear, Exposure data only measured at baseline, Exposure status not well described, Weight, height, and waist circumference were self-reported, No preregistered data analysis plan; Funding: NR
Konieczna, 2019^150^; PCS, Secondary analysis of PREDIMED trial, Spain; Analytic N=7,009; Included in meta-analysis: yes; Study purpose: To investigate how changes in the consumption of specific foods were associated with concurrent changes in weight or waist circumference; Participant characteristics at baseline: Spanish older adults; - Age: Mean (SD): 67y (6.2); Range: 55-70y; - Female: 58%; - Race/ethnicity: 100% “white, elderly Spanish”; - SEP: Higher education/technician: 7%; - Anthropometry: Body weight, kg, mean (SD): 76.7 (12.0); WC, cm, mean (SD): 100 (10); BMI, kg/m^2, mean (SD): 30.0 (3.8); Obesity prevalence: 47%; Abdominal obesity prevalence: 73%; - Physical activity: METs (min/d), mean (SD): 233 (239); - Smoking: Current smoker: 14%; - Alcohol intake: Adherence to MedDiet (14-points score), mean (SD): 9 (2); - Diet quality: Adherence to MedDiet (14-points score), mean (SD): 9 (2); - TEI: Kcal/day, mean (SD): 2239 (543); - Study beverage intake at baseline: Baseline (svg/d), mean (SD): 0.11 (0.42); Inclusion criteria: age between 55-80y, free of CVD at enrollment but at risk of CVD based on T2D diagnosis or ≥3 risk factors (hypercholesterolemia, low HDL, overweight/obesity, hypertension, current smoking or family history of premature coronary heart disease); Excluded: missing data on waist circumference, physical activity, or FFQ at baseline, total energy intake values outside predefined limits | Exposure: Soft beverages with sugar (drinks with cola, lemonades, tonic, fruit juices (bottled or canned). Exposure of interest was change in intake expressed in serving/d, calculated as the difference between yearly measured values and values from the previous year.; Comparator: Continuous, svg/d; Assessment methods and timing:; 137-item semi-quantitative FFQ; intake calculated by multiplying serving size by frequency of consumption (from never to > 6 times/d); At baseline and yearly thereafter (~5y follow-up); analyzed as change over time; Outcomes and assessment methods: Height and weight: valid measure by study staff; BMI: calculated from height and weight measurements; Waist circumference: determined midway between lowest rib and iliac crest using anthropometric tape; measured in duplicate by trained staff; average of two measurements was analyzed value; Absolute change in body weight and WC: calculated as difference between yearly measured values and values from previous year; Baseline and annually thereafter (mean follow-up 4.8y) | [underlined: ΔWC (cm) over 5y] follow-up by concurrent changes in SSB intake (svg/d), β (95% CI), generalized estimating equation; Overall: 0.08 (−0.15, 0.31), p=0.499; Men: 0.00 (−0.32, 0.32), p=0.982; Women: 0.14 (−0.18, 0.46), p=0.395; [underlined: ΔBody weight (kg) over 5y] follow-up by concurrent changes in SSB intake (svg/d), β (95% CI), generalized estimating equation; 0.07 (−0.06, 0.19), p=0.313 | Model adjustments:; - TEI: no; - Key confounders: sex, age, socioeconomic position, anthropometry at baseline, physical activity, smoking, diet quality (vegetables, sweets, low-fat milk, low-fat yogurt, snacks/fast foods/prepared dishes); - Other: Time (years, due to slight variations in period between successive visits), center, intervention group (combined MedDiets versus. control). No multi-collinearity was observed between these food groups.; Limitations:; - Did not account for key confounders: race and/or ethnicity; - No preregistered data analysis plan; Limited generalizability; Funding:; CIBER Fisiopatología de la Obesidad y Nutrición (CIBEROBN); Instituto de Salud Carlos III (ISCIII); “FOLIUM” program within the FUTURMed project; Fundación Instituto de Investigación Sanitaria Illes Balears; ERC Advanced Research Grant
Kvaavik, 2005^151^; PCS, Oslo Youth Study, Norway; Analytic N=422; Included in meta-analysis: yes; Study purpose: To investigate the tracking of sugar-sweetened, carbonated soft drinks intake from age 15 to 33 years and the association between this intake and lifestyle factors and body weight; Participant characteristics at baseline: Adults; - Age: Mean~25y (Range: 23-27y); - Female: 53%; - Race/ethnicity: NR; - SEP: NR; - Anthropometry: BMI in 1979/1981, Mean: 19.6kg/m2; - Physical activity: Leisure-time physical activity twice weekly: 46%; - Smoking: Weekly: 40%; - Alcohol intake: NR; - Diet quality: NR; - TEI: NR; - Study beverage intake at baseline: Intake in 1991 Women:; Never/seldom: 54.3%; 1-2x/wk: 21.6%; 3–6x/wk: 10.8%; 1x/d: 9.5% >1/d: 3.9%; Men:; Never/seldom: 25.6%; 1-2x/wk: 27.6%; 3–6x/wk: 25.6%; 1x/d: 9.9%; >1/d: 11.3%; Excluded: participants with anorexia, bulimia nervosa, and pregnant women; Included: participants who responded to all 3 surveys during 18-20y time period | Exposure: Sugar-sweetened carbonated soft drinks; Comparator: Categorical intake (Longterm low consumers, Inconsistent consumers, Long-term high consumers); Assessment methods and timing: 1991: one question on intake of sugarsweetened carbonated soft drinks 1999: validated semi-quantitative FFQ Participants were grouped by reported frequency of sugar-sweetened carbonated soft drinks in 1991 and 1999. Soft drink intake ≤2x/wk in 1991 and ≤3x/wk in 1999 was categorized as low intake, and intake ≥3x/wk in 1991 and ≥4x/wk in 1999 was categorized as high intake. Participants were defined as ‘long-term low consumer” if he/she reported low intake in both 1991 and 1999, a ‘long term high consumer’ for high intake in both 1991 and 1999, and an ‘inconsistent consumer’ if intake changed from high to low or vice versa between 1991 and 1999.; 1991 and 1999; Outcomes and assessment methods: Body weight and height were measured at school by project staff in 1979/1981 but were self-reported in 1999; 1979/1981, 1999 | [underlined: BMI (kg/m2)] in 1999 follow up based on intake during 1991-1999, Mean (SD); Women (n=196); Long-term consumers: 23.4 (4.1); Inconsistent consumers: 23.0 (3.9); Long-term high consumers: 24.0 (5.3); P=0.627; Men (n=192); Long-term consumers: 25.6 (3.5); Inconsistent consumers: 25.9 (4.2); Long-term high consumers: 25.3 (4.2); P=0.685; [underlined: Overweight] in 1999 follow up based on intake during 1991-1999, OR (95% CI); Women; Long-term consumers (n=116): REF; Inconsistent consumers (n=50): 1.26 (0.57, 3.08); Long-term high consumers (n=21): 1.57 (0.46, 5.33); Men; Long-term consumers (n=78): REF; Inconsistent consumers (n=66): 1.25 (0.62, 2.55); Long-term high consumers (n=40): 1.05 (0.46, 2.40); [underlined: Obesity] in 1999 follow up based on intake during 1991-1999, OR (95% CI); Women; Long-term consumers (n=116): REF; Inconsistent consumers (n=50): 1.98 (0.46, 8.41); Long-term high consumers (n=21): 0.80 (0.09, 6.85); Men; Long-term consumers (n=78): REF; Inconsistent consumers (n=66): 0.52 (0.10, 2.69); Long-term high consumers (n=40): 2.29 (0.48, 10.96) | Model adjustments:; - TEI: yes; - Key confounders: sex; anthropometry at baseline; physical activity; smoking; - Other: Dieting, energy underreporting; Limitations:; - Did not account for key confounders: age; race and/or ethnicity; SEP; diet quality; - Height and weight were selfreported; No preregistered data analysis plan; Funding:; The Norwegian Cancer Society; Norwegian Foundation for Health and Rehabilitation
Larson, 2018^50^; PCS, Project EAT (Eating and Activity in Teens and Young Adults), U.S.; Analytic N=1120 (adolescence to adulthood); 695 (adulthood); Included in meta-analysis: no; Study purpose: To identify personal, behavioral, and environmental factors that predicted healthy weight maintenance during the transition from adolescence to adulthood and as individuals progressed from the third to fourth decade of life; Participant characteristics at baseline: adolescents without overweight or obesity during transition to adulthood; - Age: ~25.3y at Time 3; Range: ~21-28y; - Female: ~57%; - Race/ethnicity: 64% white; 9% African American; 17% Asian; 3% Native American, 3% Mixed or Other ethnicity/race; 4% Hispanic; - SEP: NR; - Anthropometry: Overweight/obesity: 0%; - Physical activity: NR; - Smoking: NR; - Alcohol intake: NR; - Diet quality: NR; - TEI: NR; - Study beverage intake at baseline: NR; Exclude: those without height and weight data at ≥1 timepoint; with overweight or obesity at Time 1; women who were pregnant when they reported their adult weight at Time 3 or 4; adults with BMI <18.5 kg/m2 at Time 4 | Exposure: Sugary drinks (carbonated beverages with and without caffeine, and other sugared beverages including fruit drinks, sports drinks, and ice teas); Comparator: Continuous (svg/d); Assessment methods and timing:; Validated FFQ; Baseline measurement was during adolescence and is captured in the childhood/adolescence evidence; 10y follow-up, (Time 3, 2008-2009), and 17y follow-up (Time 4, 2015-2016); Outcomes and assessment methods: Weight and height were self-reported and used to calculate BMI. Healthy weight status (i.e., non-overweight BMI) was defined using screening guidelines: BMI <85%tile for sex and age at Time 1 and BMI <25 kg/m2 at Time 3 and Time 4.; Healthy weight maintenance from adolescence to young adulthood was defined by a non-overweight BMI at Time 1, Time 3, and Time 4.; Healthy weight maintenance in early adulthood was defined by a nonoverweight BMI; At baseline (Time 1, 1998-1999), 10y follow-up, (Time 3, 2008-2009), and 17y follow-up (Time 4, 2015-2016) | [underlined: Healthy weight maintenance] at Time 4, OR (95% CI), logistic regression; [underlined: By sugary drink intake at Time 3]; Women (n=400): 0.85 (0.62, 1.16); Men (n=295): 0.63 (0.37, 1.10); [underlined: By change in sugary drink intake from Time 3 to Time 4]; Women: 1.33 (0.86, 2.05); Men: 0.82 (0.50, 1.30) | Model adjustments:; - TEI: yes; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position, anthropometry at baseline (BMI); - Other: N/A; Limitations:; - Did not account for key confounders: physical activity, diet quality, smoking; - High attrition; Weight and height were self-reported; No preregistered data analysis plan; Funding:; NHLBI
Lim, 2021^152^; PCS, Singapore Multi-Ethnic Cohort, Singapore; Analytic N=3,064; Included in meta-analysis: yes; Study purpose: To evaluate the relationship between changes in intakes of nutrients, foods, and beverages and diet quality and long-term changes in body weight; Participant characteristics at baseline: Asian adults; - Age: ~44 (10)y; - Female: 58%; - Race/ethnicity: 52% Chinese, 23% Malay, 25% Indian; - SEP: 40% above secondary education, 40% secondary, 21% primary and below; 79% married; - Anthropometry: ~24 kg/m2; - Physical activity: ~109 MET-hr/wk; - Smoking: 81% never, 6% stopped, 13% current smokers; - Alcohol intake: AHEI-2010 score ~51; - Diet quality: AHEI-2010 score ~51; - TEI: NR; - Study beverage intake at baseline: ~0.2 svg/wk SSB; Exclude: heart disease, stroke, diabetes, cancer; <21y or >65y at baseline; extreme energy intake or non-random skip pattern in FFQ; participants with ethnicity other than Chinese, Malay, or Indian; pregnant; missing data on exposure, outcome, or covariates | Exposure: Soft drinks (including sugared fruit drinks; sugared drinks made from syrup, cordial, or sweetened canned or packet drinks; carbonated drinks with sugar; and sports/energy drinks); 1 svg = 330 mL; Comparator: Continuous (svg/d); Categorical [moderate decrease (>0.50 svg/d), small decrease (0.01-0.50 svg/d), no change to small increase (0-0.5 svg/d; moderate increase (>0.50 svg/d)]; Assessment methods and timing:; Validated FFQ representing intake over the past month; At baseline (2004-2010), and 6 (1.5)y follow-up (2011-2016); Outcomes and assessment methods: Weight, height and waist circumference (WC) were measured by study staff using standard methods; At baseline (2004-2010), and 6 (1.5)y follow-up (2011-2016) | [underlined: Change in WC (cm)] over follow-up by 1 svg/d increase of SSB, β (95% CI); 0.70 (−0.01, 1.41), p=0.055; [underlined: Change in weight (kg)] over follow-up by 1 svg/d increase of SSB, β (95% CI), linear regression; 0.69 (0.05, 1.33), p=0.036; Chinese: 0.38 (−0.45, 1.21); Malay: 0.02 (−0.67, 0.71); Indian: 2.18 (1.19, 3.18); p-interaction=0.031; Male: 0.79 (−0.27, 1.85); Female: 0.57 (−0.16, 1.31); p-interaction: 0.58; BMI <25 kg/m2: 0.58 (−0.17, 1.33); BMI >25 kg/m2: 0.78 (−0.20, 1.76); p-interaction: 0.32; [underlined: Change in weight (kg)] over follow-up by categories of changes in SSB intake, β (95% CI), linear regression; Moderate decrease: REF; Small decrease: 0.33 (−0.70, 1.37); No change to small increase: 0.30 (−0.80, 1.40); Moderate increase: 1.13 (−0.30, 2.55) | Model adjustments:; - TEI: no; - Key confounders: sex, age, race/ethnicity, SEP (education, marital status), anthropometry at baseline, physical activity, smoking, and diet quality (fruit, vegetables, whole grains, refined grains, snacks, red meat, poultry, fish and seafood, dairy, egg, soy); - Other: alcohol; Limitations:; - Did not account for key confounders:; - High attrition/missing data; No preregistered data analysis plan; Funding:; National Medical Research Council; Biomedical Research Council; Ministry of Health (Singapore); National University of Singapore; National University Health System (Singapore)
Ma, 2016^153^; PCS, Third Generation cohort of the Framingham Heart Study, U.S.; Analytic N=1,003; Included in meta-analysis: no; Study purpose: To examine the prospective association of habitual SSB intake and change in visceral adipose tissue and subcutaneous adipose tissue; Participant characteristics at baseline: Adults in the Third Generation cohort of the Framingham Heart Study; - Age: Mean=45.3y; - Female: 45%; - Race/ethnicity: 99.7% White; - SEP: NR; - Anthropometry: BMI ~27.4 kg/m2; - Physical activity: Score ~37.2; - Smoking: 9% Current smoker; - Alcohol intake: Whole grain intake (g/d): ~29 g/d; Fruit intake: ~265 g/d; Vegetable intake: ~225 g/d; - Diet quality: Whole grain intake (g/d): ~29 g/d; Fruit intake: ~265 g/d; Vegetable intake: ~225 g/d; - TEI: ~1900 kcal/d; - Study beverage intake at baseline: SSB intake: 32% Non-consumers, 20% Occasional consumers, 35% Frequent consumers, 13% Daily consumers; Included: cohort members with CT scan at baseline (2002-2005) and follow-up (2008-2011); weight < 160 kg at first and second exams (due to CT machine’s weight restrictions); age 35y (men) or 40y (women) at baseline (age for CT eligibility);; Excluded: history of bariatric surgery, hard cardiovascular disease (stroke and myocardial infarction), or cancer (excluding non-melanotic skin cancer); missing data for SSB or diet soda (n=114); missing data on covariates at baseline (n=15) | Exposure: SSB intake (caffeinated colas with sugar, caffeine-free colas with sugar, other carbonated beverages with sugar, fruit punches, lemonade, or other noncarbonated fruit drinks; did not include sports drinks, energy drinks, and sweetened teas); Comparator: Categorical intake; - Non-consumers (none to <1 svg/mo): Median 0 svg/wk; - Occasional consumers (1 svg/mo to <1 svg/wk): Median 0.5 svg/wk; - Frequent consumers (1 svg/wk to 1 svg/d): Median 3 svg/wk; - Daily consumers (≥1 svg/d): 11 svg/wk); Assessment methods and timing:; Harvard semi-quantitative FFQ (validated); Baseline; Outcomes and assessment methods: Height measured to nearest ¼ inch using vertical ruler; Weight measured with light clothes and rounded to nearest 0.5 pound. BMI calculated as kg/m2. Abdominal adiposity (visceral adipose tissue (VAT) and subcutaneous adipose tissue (SAT) measured by CT scan.; Baseline (2002-2005), ~6y follow-up (2008-2011) | [underlined: Weight, kg], Linear regression, β (95% CI) Change per frequency of SSB intake:; Non-consumers: 2.4 (1.7, 3.2); Occasional consumers: 2.8 (1.8, 3.7); Frequent consumers: 2.4 (1.7, 3.0); Daily consumers: 1.7 (0.5, 2.9); P trend = 0.26; P interaction (Sex) = 0.46; P interaction (BMI) = 0.88; P interaction (T2DM) = 0.34; [underlined: Men]; Non-consumers: 3.1 (2.0, 4.3); Occasional consumers: 2.4 (1.1, 3.7); Frequent consumers: 2.7 (1.9, 3.4); Daily consumers: 2.5 (1.2, 3.8); P trend = 0.77; [underlined: Women]; Non-consumers: 1.8 (0.8, 2.7); Occasional consumers: 2.5 (1.2, 3.7); Frequent consumers: 2.1 (0.8, 3.4); Daily consumers: 1.2 (−1.6, 4.0); P trend = 0.72 | Model adjustments:; - TEI: yes; - Key confounders: sex, age, race and/or ethnicity, anthropometry at baseline, physical activity, diet quality (Whole grains, fruit, vegetables, saturated fat, coffee, nuts, fish), smoking; - Other: Change in body weight (for change in VAT and SAT analyses); Limitations:; - Did not account for key confounders: socioeconomic position; - Follow-up time differs among participants; Exposure measured at baseline only; No preregistered data analysis plan; Funding:; NHLBI
Moshtaghian, 2021^155^; PCS, Blue Mountains Eye Study, Australia; Analytic N=1,713; Included in meta-analysis: yes; Study purpose: To investigate the association between changes in the percentage of energy intake from added sugar and changes in body weight in a cohort study of older Australians during 15 years of follow-up; Participant characteristics at baseline: adults aged ≥49y; - Age: Mean (SD): 63.8 (8.2)y; - Female: 57%; - Race/ethnicity: NR; - SEP: 61% qualification after leaving school; 69% married, 91% home owners; - Anthropometry: BMI, mean (SD): 26.2 (4.3) kg/m2 Weight, mean (SD): 72.1 (13.5) kg; - Physical activity: Mean (SD): 1446 (2404) MET; - Smoking: 12% current; - Alcohol intake: Mean (SD); Glycemic index: 56.6 (4.3); Fiber intake: 29.1 (12) g/d; % energy from added sugar: 9.4 (5.2)%; - Diet quality: Mean (SD); Glycemic index: 56.6 (4.3); Fiber intake: 29.1 (12) g/d; % energy from added sugar: 9.4 (5.2)%; - TEI: Mean (SD): 2055 (593) kcal/d; - Study beverage intake at baseline: 1.02 (1.98)% of energy from beverage added sugar; Exclude: missing FFQ and weight data; energy intakes <598 kcal or 4302 kcal; added sugar intake more than mean ± 4 SD | Exposure: Beverage sources of added sugar (including SSBs such as sweetened juices, cordial, soft drinks) as a percentage of energy intake; Comparator: Continuous (1% increase); Categorical (quartiles at each 5yr time interval); Q1: participants with the largest decrease in intake in the first, second, and third 5yr time interval.; Q2: participants in Q2 in the first, second, and third 5yr time interval.; Q3: participants in Q3 in the first, second, and third 5yr time interval.; Q4: participants with the largest increase in the first, second, and third 5yr time interval.; Assessment methods and timing:; Validated FFQ; At baseline (1992-1994), and three 5y follow-ups (1997-1999, 2002-2004, 2007- 2009); Outcomes and assessment methods: Weight measured with electronic scales. At baseline (1992-1994), and three 5y follow-ups (1997-1999, 2002-2004, 2007-2009) | [underlined: Overall 5-yearly change in weight (kg)] during 15y follow-up; [underlined: By 1% increase in energ]y from beverage sources of added sugar, β (95% CI), GEE; −0.028 (−0.141, 0.084); p-trend: 0.621; [underlined: By quartiles of change in percentage of] [underlined: energy] from beverage sources of added sugar, Mean (95% CI), GEE; Q1: 0.06 (−0.85, 0.97); Q2: 0.27 (−0.54, 1.08); Q3: 0.43 (−0.51, 1.37); Q4: 0.10 (−0.71, 0.91) | Model adjustments:; - TEI: yes; - Key confounders: sex, age, anthropometry at baseline, physical activity, smoking, diet quality (fiber intake, % energy from added sugars); - Other: diabetes, glycemic index; Limitations:; - Did not account for key confounders: race and/or ethnicity, socioeconomic position; - No preregistered data analysis plan; Funding:; Australian National Health and Medical Research Council
Mozaffarian, 2011^156^; PCS, Nurses Health Study (NHS) + NHS II + Health Professionals Follow-Up Study (HPS), U.S.; Analytic N=NHS = 50,422; NHS II = 47,898; HPS = 22,557; Included in meta-analysis: no; Study purpose: To investigate the relationship between multiple lifestyle changes, both independently and jointly, and long-term weight gain in women without obesity and men participating in three separate, prospective studies; Participant characteristics at baseline: Adults; - Age: Mean (SD):; NHS 52.2y (7.2), NHS II 37.5y (4.1), HPS 50.8y (7.5); - Female: NHS & NHS II: 100% HPS: 0%; - Race/ethnicity: Primarily white; - SEP: Primarily well-educated; - Anthropometry: Mean (SD): BMI (kg/m2), NHS 23.7 (1.4), NHS II 23.0 (2.7), HPS 24.7 (1.1); - Physical activity: MET-hr/wk, Mean (SD): NHS 14.8 (9.9), NHS II 21.6 (25.9), HPS 22.9 (15.1); - Smoking: Never smoker: 53%, Past smoker: 33%, Current smoker: 13%, Missing: 1%; - Alcohol intake: NR; - Diet quality: Mean, serv/d Fruit: ~1.5, Vegetables: ~3.5, Whole grains: ~0.6; - TEI: NR; - Study beverage intake at baseline: SSB intake, svg/d, Mean (SD): NHS 0.2 (0.2), NHS II 0.3 (0.6), HPS 0.3 (0.3); Exclude: obesity, diabetes cancer, or cardiovascular, pulmonary, renal, or liver disease at baseline; missing data on lifestyle habits; implausible energy intake, >9 blank responses on the diet questionnaire; newly pregnant during follow-up; >65y of age | Exposure: SSB (Coke, Pepsi, or other cola); Comparator: Continuous intake (svg/d); Assessment methods and timing:; Validated questionnaire; represents usual dietary intake; At baseline, every 4y over 12- to 20-y follow-up; analyzed as change over 4y intervals; Outcomes and assessment methods:; - Weight was collected via self-report from questionnaire; - At baseline, and every 2y over 12- to 20-y follow-up | [underlined: Weight change over 4y intervals up to][underlined: 20y], lb, Linear regression, β (95% CI) Concurrent SSB change:; NHS: 0.95 (0.78, 1.12), P<0.001; NHS II: 1.16 (1.01, 1.32), P<0.001; HPS: 0.88 (0.71, 1.06), P<0.001 | Model adjustments:; - TEI: no; - Key confounders: Sex, age, anthropometry at baseline, physical activity, smoking, diet quality (fruits, vegetables, whole grains, whole-fat and low-fat dairy, potato chips, potatoes/fries, refined grains, sweets and desserts, processed and unprocessed meats, trans fat, fried foods at and away from home, and other beverage types); - Other: Alcohol, television watching, sleep duration; Limitations:; - Did not account for key confounders: Race and/or ethnicity, SEP; - Self-reported weight; Funding:; NIH; Searle Scholars Program
Mullie, 2017^157^; PCS, Belgium; Analytic N=562; Included in meta-analysis: yes; Study purpose: To examine how SSB intakes influence changes in weight, according to the way SSB intakes are analysed; Participant characteristics at baseline: Adults; - Age: Mean (SD); Men: 47 (8)y; Women: 45 (8)y; Range: 18-75y; - Female: 35%; - Race/ethnicity: NR; - SEP: NR; - Anthropometry: Mean (SD) BMI, kg/m^2^, Men: 25.4 (2.7), Women: 23.4 (3.0) Weight, kg: Men: 79.3 (10.1), Women: 63.9 (8.7); - Physical activity: Physical activity level (PAL), Mean (SD), Men: 1.8 (0.2), Women: 1.7 (0.2) PAL 1.70-1.99 = moderately active; - Smoking: Current smoker, % Men: 13%, Women: 13%; - Alcohol intake: HEI Score by SSB intake category, Mean (SD); Never: 49 (10), Low: 45 (9), Moderate: 40 (9) High: 33 (5); - Diet quality: HEI Score by SSB intake category, Mean (SD): Never: 49 (10), Low: 45 (9), Moderate: 40 (9), High: 33 (5); - TEI: Mean (SD), kcal/d; Men: 2,590 (675), Women: 2026 (499); - Study beverage intake at baseline:; Nonconsumers: 66%; Consumers: 34%; In consumers, SSB Mean TEI %; Men: 4.8%, Women: 2.4%; Exclude: missing data; loss to follow up | Exposure: SSBs: Beverages containing added caloric sweeteners such as sucrose and/or high-fructose corn syrup; Comparator: Continuous intake; Categorical intake:; No consumption,; Low daily consumption (<1 glass or 200mL),; Moderate daily consumption (1-3 glasses or 200-700mL),; High daily consumption (>3 glasses or ≥700mL); Assessment methods and timing:; 3-day dietary records; Baseline, 10y follow up; Outcomes and assessment methods: Anthropometric measurements performed by trained staff using standardized techniques; Baseline, 10y follow up | [underlined: Weight change over 10y], β (95% CI), pvalue; [underlined: Baseline SSB, categorical]:; No consumption (n=371): REF; Low (n=82): 0.157 (−1.025, 1.340), p = 0.794; Moderate (n=91): −0.161 (−1.333, 1.012), p = 0.788; High (n=18): 4.338 (1.891, 6.786), p=0.001; [underlined: Baseline SSB, continuous]:; 0.190 (−0.198, 0.578), p = 0.335; SSB change (ml/d) over 10y (residuals):; 0.002 (−0.001, 0.005), p = 0.13 | Model adjustments:; - TEI: yes; - Key confounders: sex, age, anthropometry at baseline, physical activity; - Other: N/A; Limitations:; - Did not account for key confounders: Race and/or ethnicity, SEP, smoking, diet quality; - High attrition with no information on non-completers; No preregistered data analysis plan; Funding:; Policy Research Centre Sport (Flemish government)
Nooyens , 2005^158^; PCS, Doetinchem Cohort Study, The Netherlands; Analytic N=288; Included in meta-analysis: yes; Study purpose: To study changes in lifestyle in relation to changes in body weight and waist circumference associated with occupational retirement in men; Participant characteristics at baseline: men (5065); - Age: mean (SD) ~53 (2)y; - Female: 0%; - Race/ethnicity: NR; - SEP: Higher vocational education or university: ~45% of those with sedentary occupations; ~17% of those with active occupations; 61% currently working; 39% retired; - Anthropometry: BMI ~26 kg/m2; 10% with obesity, 34% with abdominal obesity; - Physical activity: 46% with active occupations; - Smoking: ~75% nonsmoker; - Alcohol intake: NR; - Diet quality: NR; - TEI: NR; - Study beverage intake at baseline: NR; Inclusion: participants in original cohort; Excluded: aged <50 or >65y; incomplete data on body weight and waist circumference; cancer, cardiovascular disease, diabetes, waist circumference <79 cm at baseline | Exposure: Sugared soft drinks; Comparator: Continuous intake (glasses/d); Assessment methods and timing:; Validated semi-quantitative FFQ assessing habitual consumption during the previous year; Baseline and 5y follow-up; analyzed as change over time; Outcomes and assessment methods: Body weight, height and waist circumference (cm) were measured at the municipal health centre; Baseline and 5y follow-up | [underlined: Change in WC (cm/yr)] by change in SSB frequency (glasses/d): linear regression; β=0.06 p=0.47; [underlined: Change in body weight (kg/yr)] by change in SSB frequency (glasses/d): linear regression; β=0.12 p=0.05 | Model adjustments:; - TEI: yes (for WC but not weight); - Key confounders: sex, age, anthropometry at baseline, physical activity, smoking, diet quality (fruit); - Other: retirement status; type of job; interaction between retirement and type of job; fruit, fiber density; potatoes (in weight analysis); pasta, alcoholic beverages, carbohydrate (in waist circumference analysis); Limitations:; - Did not account for key confounders: race and/or ethnicity, SEP; - Exposure not well defined; no information on non-completers; No preregistered data analysis plan; Funding:; Ministry of Health, Welfare and Sport of The Netherlands; National Institute for Public Health and the Environment; Netherlands Heart Foundation
Odegaard, 2010^159^; PCS, Singapore Chinese Health Study, Singapore; Analytic N=43,580; Included in meta-analysis: no; Study purpose: To examine the association between soft drinks and juice and the risk of type 2 diabetes among Chinese Singaporeans; Participant characteristics at baseline: Adults; - Age: Mean (SD), 54.8 (7.5); Range 45-74y; - Female: ~48%; - Race/ethnicity: 100% Chinese; - SEP: Secondary education: 33%; - Anthropometry: BMI Mean: 23kg/m2; - Physical activity: Moderate activity, Mean: ~50min/wk; - Smoking: Ever: 26%; - Alcohol intake: NR; - Diet quality: NR; - TEI: Mean~1600 kcal/d; - Study beverage intake at baseline: SSB intake; Never or hardly ever (0 serv): 73.6%; Monthly (1-3 svg/mo): 10.4%; 1 svg/wk: 5.5%; ≥2 svg/wk: 10.6%; Fruit juice/juice drink intake; Never or hardly ever (0 serv): 82%; Monthly (1-3 svg/mo): 10%; 1 svg/wk: 4%; ≥2 svg/wk: 4%; Excluded: participants who died before follow-up interview; those who reported baseline diabetes (or unclear diabetes status), cancer, heart disease, or stroke; those who reported implausibly high (>5000kcal) or low (600kcal) energy intakes, or were lost to follow-up | Exposure: SSB intake (soft drinks such as Coca-Cola and 7UP; 1 glass = 237mL or ~1cup); & (separate exposure); Fruit and vegetable juices (1 glass = 237mL or ~1cup); unclear if 100% juice; Comparator: Categorical intake (Never or hardly ever (0 serv, Ref); Monthly (1-3 serv/mo); 1 serv/wk; ≥2 serv/wk); Assessment methods and timing:; Validated FFQ; represents usual intake over the past year; Baseline; Outcomes and assessment methods: Weight and height were self-reported BMI calculated as kg/m2; Baseline, follow-up (average 5.7y later) | [underlined: Weight change over ~5.7y (kg)], Linear Regression, β, p-value; SSB intake at baseline:; <1 svg/wk (combined category): REF ≥2 svg/wk: 0.53, P<0.001; [underlined: Weight change over ~5.7y (kg)], Linear Regression, β, p-value; Juice intake at baseline: NS, Data NR | Model adjustments:; - TEI: no; - Key confounders: sex; age; race and/or ethnicity; SEP; anthropometry at baseline; smoking; diet quality (fruit & vegetable intake); - Other: Fiber, alcohol, dialect, year of interview, person-years, total intake (g/d) of dairy, meat, candy, desserts, saturated fat, juice, coffee; Limitations:; - Did not account for key confounders: physical activity; - Participants who were diseased at baseline or who died between assessments were excluded; Categories of beverage intake measured vary from those used in analyses; Majority of participants consumed no juice; Exposure data only measured at baseline; Missing data may have differentially affected exposure groups; Height and weight were self-reported; No preregistered data analysis plan; Funding:; NIH
Olsen, 2016^160^; PCS, Danish part of Monitoring Trends and Determinants of Cardiovascular Disease (MONICA) + Diet, Cancer, and Health (DCH) study + Inter99 clinical trial study, Denmark; Analytic N=MONICA: 1,257; DCH: 2,167; Included in meta-analysis: yes; Study purpose: To examine the interactions between a molecular genetic predisposition to various aspects of obesity and the consumption of soft drinks in relation to changes in adiposity measures; Participant characteristics at baseline: adult; - Age: ~48y; - Female: ~51%; - Race/ethnicity: NR; - SEP: ~31% Primary school or less; - Anthropometry: Weight ~78 kg; - Physical activity: 15% Most sedentary group; - Smoking: ~35% Never smokers; - Alcohol intake: NR; - Diet quality: NR; - TEI: ~2151.0 kcal/d; - Study beverage intake at baseline: g/d, Median (5th%, 95th%); Soft drink intake:; MONICA: 0 (0, 250); DCH: 10.5 (0.3, 200.3); Inter99: 16.4 (0, 500); Inclusion: available information on baseline intake of soft drinks, measurements of height and BW at baseline and follow-up, information on SNPs associated with BMI, WC, or WHRBMI, and information on potential confounders; Exclusion: NR | Exposure: Soft drink intake with caloric sweeteners (1 svg= 200 g/d); Comparator: continuous (svg/d); Assessment methods and timing:; Validated FFQ (in DCH and Inter99) and 7d food record (in MONICA) with unclear validation; represents usual intake in previous year or month; At baseline; Outcomes and assessment methods: Weight and height were self-reported reported in DCH, and measured according to baseline procedures (in MONICA and Inter99); Waist circumference (WC) was selfreported reported in DCH after receipt of instructions at umbilicus level; for Inter99, WC was measured horizontally midway between lower rib margin and iliac crest to nearest 1 cm; WC was not measured in MONICA; At baseline, and follow-up (varied) | [underlined: WC change (adjusted for BMI), cm/y], Annual change per svg/d increase, Linear regression, β (95% CI); TEI Unadjusted; DCH: −0.02 (−0.13, 0.08), P=0.69; Inter99: 0.05 (−0.09, 0.20), P=0.46; TEI Adjusted; DCH: −0.02 (−0.13, 0.08), P=0.67; Inter99: 0.09 (−0.06, 0.24), P=0.26; [underlined: Weight change, kg/y], Annual change per svg/d increase, Linear regression, β (95% CI); TEI Unadjusted; MONICA: 0.04 (−0.06, 0.14), P=0.45; DCH: 0.10 (0.01, 0.18), P=0.02; Inter99: −0.03 (−0.19, 0.13), P=0.70; TEI Adjusted; MONICA: 0.05 (−0.05, 0.14), P=0.38; DCH: 0.12 (0.03, 0.20), P=0.01; Inter99: −0.02 (−0.19, 0.15), P=0.82 | Model adjustments:; - TEI: yes and no; - Key confounders: sex, age, socioeconomic position, anthropometry at baseline, physical activity, smoking; - Other: alcohol, menopausal status (in women); Limitations:; - Did not account for key confounders: race and/or ethnicity, diet quality; - No information on non-completers, Methods of exposure assessment were not similar; unclear validation of method in MONICA, Exposure measured only at baseline, Methods of outcome assessment were not similar; weight and height was selfreported in DCH, No preregistered data analysis plan; Funding:; Danish Council for Strategic Research; Danish Cancer Society; Danish Medical Research Council; Danish Centre for Evaluation and Health Technology Assessment; Novo Nordisk; Copenhagen County; Danish Heart Foundation; Danish Pharmaceutical Association; Augustinus Foundation; Henriksen Foundation; Becket Foundation
Palmer, 2008^161^; PCS, Black Women’s Health Study (BWHS), U.S.; Analytic N=42,821; Included in meta-analysis: no; Study purpose: To examine the association between consumption of sugar-sweetened beverages, weight gain, and incidence of type 2 diabetes mellitus in African American women; Participant characteristics at baseline: Adults, women; - Age: Range: 21-69y; - Female: 100%; - Race/ethnicity: Black: 100%; - SEP: Education ≤12y: 15%; - Anthropometry: BMI, Mean: 28kg/m2; - Physical activity: ≥1hr/wk: 50%; - Smoking: Current: 18%; - Alcohol intake: NR; - Diet quality: NR; - TEI: NR; - Study beverage intake at baseline: Sweetened fruit drinks at baseline; <1 serv/wk: 36.1%; 2-6 serv/wk: 32.0%; ≥1 serv/d: 31.9%; Sugar-sweetened soft drinks at baseline; <1 serv/wk: 59.1%; 2-6 serv/wk: 23.9%; ≥1 serv/d: 17.0%; Excluded: participants with reported diabetes, gestational diabetes, myocardial infarction or stroke, or cancer at baseline; if they were pregnant at baseline; if they were <30y at end of follow-up; if data on height or weight were missing at baseline; if they did not complete dietary questionnaire or left more than 10 dietary questions blank; if they had implausible energy intake value or had missing data on soft drink consumption in 1995 if they had missing data on soft drink consumption in 1995 (n=417). After exclusions, the final analysis cohort comprised 43,960 women. | Exposure: Sweetened fruit drinks (fortified fruit drinks, Kool-Aid, and fruit juices other than orange or grapefruit juice; 1 svg=6oz); Sugar-sweetened soft drinks (1 svg=12oz); Comparator: Categorical intake (<1 serv/wk, 2-6 serv/wk, ≥1 serv/d); Assessment methods and timing:; Validated FFQ representing usual intake Baseline, 6y follow up; analyzed as change over time; Outcomes and assessment methods:; Height and weight self-reported (height only at baseline, weight at baseline and follow ups); BMI calculated as kg/m2; Baseline, every 2y after (10y of follow-up data) | [underlined: Weight change over 6y], by change in sugar-sweetened soft drink intake from baseline to 6y follow up, Mean weight gain, kg (SD):; ≥1 serv/d to ≤1 serv/wk: (n=1,472): 4.1 (0.22), REF; ≤1 serv/wk to ≤1 serv/wk (n=14,246): 4.9 (0.07), p=NR; ≥1 serv/d to ≥1 serv/d (n=2,032): 5.8 (0.19), p=NR; ≤1 serv/wk to ≥1 serv/d (n=880): 6.8 (0.28), p<0.001; All others: (n=11,057): 5.5 (0.08); [underlined: Weight change over 6y], Multivariate models; Change in sweetened fruit drinks intake from baseline to 6y follow up, Mean weight gain, kg (SD):; ≥1 serv/d to ≤1 serv/wk: (n=3,198): 4.6 (0.15), REF; ≤1 serv/wk to ≤1 serv/wk (n=7,271): 5.2 (0.10); ≥1 serv/d to ≥1 serv/d (n=3,426): 5.5 (0.14); ≤1 serv/wk to ≥1 serv/d (n=1,069): 5.4 (0.26); All others: (n=14,448): 5.3 (0.07), all p=NS | Model adjustments:; - TEI: no; - Key confounders: sex; age; race and/or ethnicity; SEP; anthropometry at baseline; physical activity; smoking; diet quality (red meat, processed meat, cereal fiber, and coffee); - Other: Family history of diabetes; glycemic index; Limitations:; - Did not account for key confounders:; - Selection into study related to outcome (e.g., disease prevalance at baseline); Smaller sample size for juice data, likely due to missing data but unclear; Missing data may have differentially affected exposure groups; Height and weight were self-reported; No preregistered data analysis plan; Funding:; NCI; NIDDK
Pan, 2013^175^; PCS, Nurses Health Study (NHS) + NHS II + Health Professionals Follow-up Study (HPS) , U.S.; Analytic N=NHS = 50,013; NHS II = 52,987; HPS = 21,988; Included in meta-analysis: yes; Study purpose: To examine the long-term relationship between changes in water and beverage intake and weight change; Participant characteristics at baseline: Adults; - Age: Mean ~47y; - Female: NHS & NHS II: 100% HPS: 0%; - Race/ethnicity: Primarily white; - SEP: Primarily well-educated; - Anthropometry: Overweight: 31%, Obesity: 17%, BMI Mean: ~25 kg/m2; - Physical activity: Mean~18 MET-hr/wk; - Smoking: Never smoker: 54%, Past smoker: 33%, Current smoker: 13%; - Alcohol intake: Mean, serv/d SSB: ~0.4; - Diet quality: Mean, serv/d SSB: ~0.4; - TEI: NR; - Study beverage intake at baseline: SSB intake, svg/d, Mean (5th-95th%): NHS 0.24 (0-1.07), NHS II 0.46 (0-2.5), HPS 0.37 (0-1.36); Exclude: missing weight, beverage, or lifestyle habits data; inadequate diet data; implausible TEI; >65y of age; diabetes, cancer, cardiovascular, pulmonary, renal or liver disease; pregnancy during follow up | Exposure: SSB intake (“Coke, Pepsi or other cola with sugar”, “caffeine-free Coke, Pepsi or other cola with sugar”, “other carbonated beverages with sugar”, and “Hawaiian punch, lemonade or other non-carbonated fruit drinks”); Comparator: Continuous intake (serv/d); Assessment methods and timing:; Validated FFQ; represents usual intake of foods and beverages; At baseline, every 4y over 16- to 20-y follow-up; analyzed as change over 4y intervals; Outcomes and assessment methods:; Weight was collected via self-report from questionnaire; At baseline, and every 2y over 16- to 20-y follow-up | [underlined: Weight change over ~20y] (by 4-year assessment intervals), kg, Linear regression, β (95% CI); Change per svg/d increase over each 4y period:; NHS: 0.36 (0.30, 0.41), P=NR; NHS II: 0.47 (0.42, 0.52), P=NR; HPS: 0.25 (0.19, 0.31), P=NR; P=0.13; NHS II: 0.47 (0.42, 0.52), 0.42 (0.28, 0.56),; P=0.006; HPS: 0.34 (0.23, 0.44), 0.21 (0.13, 0.29),; NHS: 0.13 (0.07, 0.18), 0.40 (0.31, 0.49), 0.56 (0.39, 0.72), P<0.001; NHS II: 0.15 (0.11, 0.20), 0.53 (0.44, 0.62), 0.81 (0.68, 0.94), P<0.001; HPS: 0.12 (0.05, 0.19), 0.27 (0.18, 0.36), 0.45 (0.16, 0.74), P<0.001 | Model adjustments:; - TEI: no; - Key confounders: Sex, age, anthropometry at baseline, physical activity, smoking, diet quality (fruits, vegetables, whole grain, refined grain, potatoes, potato chips, red meat, other dairy products, sweets and deserts, nuts, fried foods, and trans fat, and other beverage types); - Other: Alcohol, protein, television watching; Limitations:; - Did not account for key confounders: Race and/or ethnicity, SEP; - Self-reported weight; Funding:; NIH
Partridge, 2016^162^; PCS (mediation analysis from trial data), ‘TXT2BFiT’ mHealth intervention, Australia; Analytic N=123; Included in meta-analysis: yes; Study purpose: To examine whether prevention of weight gain was associated with individual factors, such as eating and physical activity behaviors; Participant characteristics at baseline: Young adults at risk of weight gain; - Age: 29% 18-24y, 22% 25-29y, 49% 30-35y; - Female: 59%; - Race/ethnicity: 67% English; 33% Other; - SEP: 60% ≥University bachelor degree; 93.5% Highest quintiles; - Anthropometry: Weight, kg ~79 (12.6); BMI range 23-32; - Physical activity: 6.64 (3.33) d/wk; ~1620 MET min/wk; - Smoking: NR; - Alcohol intake: Intake scored 1 (0 svg/d) through 7 (≥6 svg/d); Fruit: ~2.5; Vegetable: ~3.3; - Diet quality: Intake scored 1 (0 svg/d) through 7 (≥6 svg/d); Fruit: ~2.5; Vegetable: ~3.3; - TEI: NR; - Study beverage intake at baseline: SSB intake >1L/wk: 100%; Intake scored 1 (0 svg/wk) through 5 (≥3000 mL/wk) with a difference of 1 unit representing 1L/wk; SSB: ~4.15; Include: BMI 23.0-24.9 with 2kg weight gain in past 12mo, BMI 25.0-31.9, not meeting daily F&V intake, SSB >1L/wk, energy-dense meals away from home (i.e., take-out food) >1x/wk, and/or <60 min/d moderate physical activity | Exposure: An mHealth intervention consisting of 5 personalized coaching calls with a dietitian, 8 weekly gender and stage-of-change specific text messages targeting fruit and vegetable consumption, take-out meal consumption, SSB consumption and physical activity levels, weekly emails and access to smartphone applications and study website. Maintenance phase lasted 6mo and participants received two booster coaching calls, monthly text messages and emails and had ongoing access to the smartphone applications and website.; Comparator: Change in SSB intake (continuous, svg/d); Assessment methods and timing:; Validated short questions on usual weekly intake of SSB at baseline, end of intervention (3mo), 6mo follow up; Baseline, 3mo; Outcomes and assessment methods: Weight was self-reported via online survey Baseline, end of intervention (3mo), 6mo follow up | [underlined: Change in weight]: Mediation analysis of the effect of intervention on SSB score (higher score = greater reduction in intake), Linear regression, β (SE); At 3mo: −0.50 (0.27), P=0.07; At 9mo: −0.61 (0.26), P=0.02 | Model adjustments:; - TEI: no; - Key confounders: Sex, anthropometry at baseline; - Other: Allocation, general practitioner practice; Limitations:; - Did not account for key confounders: Age, race and/or ethnicity, SEP, physical activity, smoking, diet quality; - Self-reported outcome data; analysis plan unclear in trial registry; Funding:; Hospitals Contribution Fund Medical Research Foundation; Commonwealth Government of Australia
Qi, 2012^163^; PCS, Nurses Health Study (NHS) + Health Professionals Follow-Up Study (HPFS) + Women’s Genome Health Study (WGHS), U.S.; Analytic N=NHS: 6,934; HPFS: 4,423; WGHS: 21,740; Included in meta-analysis: no; Study purpose: To analyze the interaction between genetic predisposition and the intake of sugar-sweetened beverages in relation to bodymass index and obesity risk; Participant characteristics at baseline: Adult health professionals; - Age: Mean~51y; - Female: 87%; - Race/ethnicity: 100% European ancestry; - SEP: Occupation: 100% health professionals; - Anthropometry: BMI: Mean~25 kg/m2; - Physical activity: Mean~16 MET-hr/wk; - Smoking: Current smoker ~9%; - Alcohol intake: NR; - Diet quality: Alternative Healthy Eating Index (AHEI) score: NHS: ~28, HPFS: ~43; - TEI: ~1700 kcal/d; - Study beverage intake at baseline: SSB intake:; - NHS: <1 svg/mo (41%), 1-4 svg/mo (26%), 2-6 svg/wk (22%), ≥1 svg/d (12%); - HPFS: <1 svg/mo (37%), 1-4 svg/mo (24%), 2-6 svg/wk (30%), ≥1 svg/d (9%); - WGHS: <1 svg/mo (45%), 1-4 svg/mo (22%), 2-6 svg/wk (25%), ≥1 svg/d (8%); Included: NHS: female registered nurses, 34 to 59y at baseline (1980), European ancestry HPFS: male health professionals 40 to 75y at baseline (1986); genotype data based on GWAS available; European ancestry WGHS: initially healthy female health professionals 45y or older at baseline (1992-1995), no major chronic diseases at baseline, confirmed selfreported European ancestry, available genotype data and responses to FFQ, no diabetes at baseline; Excluded: obesity at baseline | Exposure: SSB intake (caffeinated colas, caffeine-free colas, carbonated non-cola soft drinks, and non-carbonated SSBs (fruit punches, lemonades, and other fruit drinks)); Comparator: Continuous intake and categorical intake (<1svg/mo, 1-4 svg/mo, 2-6 svg/wk, ≥1 svg/d); Assessment methods and timing:; Validated semi quantitative FFQ; At baseline, and every 4y after for NHS and HPFS; At baseline only for WGHS; Outcomes and assessment methods: Height and weight were self-reported and highly correlated (0.97) with measured values in a sub-sample; BMI calculated as kg/m2. Obesity (BMI>30 kg/m2); NHS: At baseline, and every 4y follow-up assessment up to 18y; HPFS: At baseline, and every 4y follow-up assessment up to 12y; WGHS: At baseline, and 6y follow-up | [underlined: Data represent the difference in BMI for each increment of 10 risk alleles], stratified by beverage intake, P for interaction (genetic predisposition score* intake); [underlined: Increase in BMI], Linear regression, β (SE); NHS (n=6934); <1 svg/mo: 1.18 (0.17); 1-4 svg/mo: 1.56 (0.16); 2-6 svg/wk: 1.78 (0.22); ≥1 svg/d: 2.03 (0.38), P interaction: 0.008; HPFS (n=4432); <1 svg/mo: 0.77 (0.19); 1-4 svg/mo: 0.43 (0.20); 2-6 svg/wk: 1.08 (0.19); ≥1 svg/d: 1.54 (0.37), P interaction: 0.02; WGHS (n=21,740); <1 svg/mo: 1.39 (0.13); 1-4 svg/mo: 1.64 (0.19); 2-6 svg/wk: 1.90 (0.18); ≥1 svg/d: 2.53 (0.36), P interaction: 0.001; [underlined: Incident Obesity], Cox proportional hazard, RR (95% CI); NHS (n=6402): Data NR,; P for interaction=0.03; HPFS (n=3889): Data NR,; P interaction=0.20; WGHS (n=18,127):; <1 svg/mo: 1.40 (1.19, 1.64); 1-4 svg/mo: 1.50 (1.16, 1.93); 2-6 svg/wk: 1.54 (1.21, 1.94); ≥1 svg/d: 3.16 (2.03, 4.92); P for interaction =0.007; [underlined: Difference in BMI], per 1 svg/d of SSB according to genetic predisposition score quartile, kg/m^2^, General linear model; NHS: Data NR, P for interaction<0.001; HPFS: Data NR, P for interaction=0.09; WGHS: Data NR; P for interaction=0.003; [underlined: BMI], Pooled across cohorts, β (SE); Genetic-predisposition score,; Highest quartile: 0.44 (0.15); P = 0.003); Lowest quartile: −0.07 (0.08); P = 0.36; P<0.001 for interaction | Model adjustments:; - TEI: yes; - Key confounders: sex, age, race and/or ethnicity, anthropometry at baseline, physical activity, diet quality (AHEI score, for NHS and HPFS), smoking; - Other: Source of genotyping data or eigenvectors derived from GWAS, time spent watching television (for NHS and HPFS), geographic region (for WGHS); Limitations:; - Did not account for key confounders: SEP; - Weight and height selfreported; No preregistered data analysis plan; Funding:; NIH; Merck Research Laboratories; American Heart Association; Harvard Glaucoma Center of Excellence; Amgen
Romaguera, 2011^164^; PCS, European Prospective Investigation into Cancer and Nutrition (EPIC) study, DiOGenes (Diet, Obesity, and Genes) project, Italy, UK, The Netherlands, Germany, Denmark; Analytic N=48,631; Included in meta-analysis: yes; Study purpose: To ascertain the association of food groups/items consumption on prospective annual changes in “waist circumference for a given BMI”, a proxy for abdominal adiposity; Participant characteristics at baseline: Adults; - Age: 20-60y; - Female: 60%; - Race/ethnicity: NR; - SEP: NR; - Anthropometry: NR; - Physical activity: NR; - Smoking: NR; - Alcohol intake: Mean (SD), g/d Fruits: ~180; Vegetables: ~170; Soft drinks: ~900; - Diet quality: Mean (SD), g/d; Fruits: ~180; Vegetables: ~170; Soft drinks: ~900; - TEI: NR; - Study beverage intake at baseline: Soft drink intake, g/d, Mean (SD): Men, 959.76 (501.82), Range=139.59-1138.79; Women, 863.22 (525.00), Range=154.84-1122.60; Exclude: no blood sample data, pregnancy, missing diet or anthropometric data, highest and lowest 1% of TEI:energy requirement ratio, chronic disease (cancer, CVD, diabetes) at baseline or follow up, unrelistic anthropometric measurements, baseline age >60y or follow-up age >65y, missing data on smoking or change in smoking status from baseline to follow up | Exposure: Soft drinks; Comparator: Continuous, 100 kcal/d; Assessment methods and timing:; Country-specific validated FFQ; represents usual food intakes; Baseline; Outcomes and assessment methods:; - Weight and height measured using standard protocol or via self-report; - Waist circumference (WC) measured either midway between the lowest rib and iliac crest, at the narrowest torso circumference, or via self-report; - BMI calculated as weight (kg) divided by height (m) squared; - Waist circumference for a given body mass index (WCBMI) calculated as the residual values from gender- and centrespecific regression equations of WC on BMI using baseline and follow-up values of WC and BMI; Baseline, 5.5y follow up | [underlined: ∆WCBMI (Waist circumference for a given body mass index), cm/y];; Association between soft drink intake and annual change in WC for given BMI; β2 (95% CI), Linear regression; All: 0.04 (0.02, 0.07), P=0.002; Men: 0.02 (0.00, 0.04), P=0.018; Women: 0.05 (0.02, 0.09), P=0.007; Interaction by gender: NS | Model adjustments:; - TEI: yes; - Key confounders: Sex, age, race and/or ethnicity, SEP, anthropometry at baseline, physical activity, smoking; - Other: Alcohol, follow-up duration, menopausal status and hormone replacement therapy use (in women); Limitations:; - Did not account for key confounders: Diet quality; - Exposure measured at baseline only; excluded participants with chronic disease at follow up; Funding:; European Union; Danish Strategic Research Council
Schulz, 2002^165^; PCS, European Prospective Investigation into Cancer and Nutrition (EPIC) - Potsdam cohort, Germany; Analytic N=17,369; Included in meta-analysis: no; Study purpose: To examine the effect of food group intake on subsequent 2-y weight change; Participant characteristics at baseline: Adults; - Age: Men: 52 (8)y; Women: 49 (9)y; - Female: 63%; - Race/ethnicity: NR; - SEP: University education: 70% men, 60% women; - Anthropometry: Men: BMI 27.1 (3.6) kg/m2; Women: BMI 25.8 (4.6) kg/m2; - Physical activity: 11 (7) hr/wk leisure time physical activity; - Smoking: Nonsmokers: 100%; - Alcohol intake: NR; - Diet quality: NR; - TEI: NR; - Study beverage intake at baseline: NR; Inclusion: nonsmokers at baseline who were never smokers or who had quit smoking 2 y ago;; Exclusion: participants using appetitesuppressing drugs, subjects with incident diseases (cancer, diabetes mellitus, myocardial infarction, stroke, chronic colitis, immobilizing fractures) and women who were pregnant or postpartum (i.e., either still breast-feeding or delivery within the last 12 mo) at baseline or at follow-up | Exposure: Soft drinks (Mineral and tap water, fruit juices, lemonade, cola, multivitamin drinks); Comparator: Continuous intake, g/d; Assessment methods and timing:; Self-administered, valid FFQ; Dietary changes occurring between baseline and follow-up were assessed once with the self-administered follow-up questionnaire. Subjects were asked whether they changed their dietary habits (profoundly, partly or not) after baseline.; Baseline, and once before follow-up asked if dietary habits changed; Outcomes and assessment methods: Baseline body weight measured by a trained technician using a calibrated scale to the nearest 0.1 kg. Weight at follow-up was self-reported (follow-up questionnaire).; Different follow-up times were taken into account by calculating weight change per years of follow-up.; Weight change per yer was used to categorize participants into 5 weight change categories: large weight gain (≥2kg/y), small weight gain (1-2kg/y), weight maintenance (REF), small weight loss (−2 to −1kg/y), and large weight loss (≤-2kg/y).; Baseline, and mean follow-up 2.2y (range: 0.6-5.4y) | [underlined: Weight change over ~2y], by SSB intake at baseline, OR (95% CI), p-value; [underlined: Men]; Stable weight (±1 kg/y; 55.8%): REF; Large wt gain (≤2 kg/y; 7.2%): 1.03 (1.01, 1.05), p>0.05; Small wt gain (+1-2 kg/y; 12.9%): 1.01 (0.99, 1.02), p=NS; Small wt loss (−2-1 kg/y; 14.4%): 1.02 (1.00, 1.04), p<0.05; Large wt loss (≤ −2 kg/y; 9.7%): 1.03 (1.01, 1.05), p<0.05 1.02), p=NS; [underlined: Women]; Stable weight (±1 kg/y; 58.0%): REF; Large wt loss ((≤2 kg/y; 6.1%): 1.01 (0.99, 1.02), p=NS; Small wt gain (+1-2 kg/y; 11.5%): 1.00 (0.99, 1.01), p=NS; Small wt loss (−2-1 kg/y; 14.0%): 1.00 (0.99, 1.01), p=NS; Large wt loss (≤ −2 kg/y; 10.4%): 1.02 (1.00, 1.03), p<0.05 | Model adjustments:; - TEI: no; - Key confounders: sex; age; SEP (education); anthropometry at baseline; physical activity; smoking; - Other: Dietary changes; Medications affecting body weight, previous weight changes, life and health satisfaction, prevalent diseases, menopausal status (women); Limitations:; - Did not account for key confounders: race and/or ethnicity; diet quality; - Selection into study related to exposure and outcome; Start of follow-up and exposure may not coincide; Exposure includes water and juice; No information on non-completers; Outcome (change in weight) was based on self-reported weight at follow-up; No preregistered data analysis plan; Funding:; German Cancer Aid Grant; European Community grant
Schulze, 2004^166^; PCS, Nurses’ Health Study II, U.S.; Analytic N=51,603; Included in meta-analysis: no; Study purpose: To examine the association between consumption of sugar-sweetened beverages and weight change and risk of type 2 diabetes in women; Participant characteristics at baseline: Adult female nurses; - Age: Mean ~36y (24-44y); - Female: 100%; - Race/ethnicity: NR; - SEP: Occupation: 100% healthcare professionals; - Anthropometry: Mean BMI ~24.4 kg/m2; - Physical activity: ~19 METs/wk; - Smoking: 12% current smokers; - Alcohol intake: Cereal fiber: ~5.5 g/d Total fat intake: ~31% of total energy intake; - Diet quality: Cereal fiber: ~5.5 g/d Total fat intake: ~31% of total energy intake; - TEI: Mean ~1800 kcal/d; - Study beverage intake at baseline: SSSD intake at baseline: 53.9% <1/mo, 25.6% 1-4/mo, 10.9% 2- 6/wk, 9.5% ≥1/d; Fruit punch intake: NR; Included: female nurses aged 24 to 44y at study initiation (1989).; Excluded: missing dietary questionnaire in 1991 or >9 items on FFQ left blank; implausible total energy intake (< 500 kcal/d or >3500 kcal/d); history of diabetes, cancer (except nonmelanoma skin cancer), or CVD at baseline; no data on physical activity in 1991 questionnaire, missing SSB intake information, history of diabetes or CVD before 1995 or reported cancer diagnosis (except nonmelanoma skin cancer) on any questionnaire, missing body weight information no data on physical activity assessed in 1997. | Exposure: Sugar-sweetened soft drink consumption (SSSD: Coke, Pepsi, or other cola with sugar; caffeine-free Coke, Pepsi, or other cola with sugar; other carbonated beverages with sugar); & (separate exposure); Fruit punch; Comparator: Categorical intake [Consistent low (≤1/wk), Consistent high (≥1/d), Low to high (≤1/wk to ≥1/d), High to low (≥1/d to ≤1/wk), Other]; Assessment methods and timing:; Validated semi-quantitative FFQ; represents intake over previous year Baseline (1991), 4y follow-up (1995); Outcomes and assessment methods:; Height measured via self-report at baseline only, Weight measured via selfreport. BMI calculated as kg/m2; Baseline (1991), 4y follow-up (1995) | [underlined: Weight (kg)], Mean (SE); [underlined: SSB change from 1991-1995]; Low to high (REF, n=1007): 4.49 (0.19); Consistent low (n=38,737): 3.22 (0.03), P<0.001; Consistent high (n=2366): 3.11 (0.13), P<0.001; High to low (n=1020): 1.56 (0.19), P<0.001; Other (n=8473): 3.00 (0.07), P<0.001; [underlined: SSB change from 1995-1999]; Low to high (REF, n=765): 4.20 (0.22); Consistent low (n=39,279): 2.04 (0.03), P<0.001; Consistent high (n=2340): 2.21 (0.13), P<0.001; High to low (n=1107): 0.15 (0.18), P<0.001; Other (n=8112): 2.10 (0.07), P<0.001; [underlined: BMI (kg/m2)], Mean (SE); [underlined: SSB change from 1991-1995]; Low to high (REF, n=1007): 1.65 (0.07); Consistent low (n=38,737): 1.18 (0.01),; P<0.001; Consistent high (n=2366): 1.15 (0.05),; P<0.001; High to low (n=1020): 0.57 (0.07), P<0.001; Other (n=8473): 1.11 (0.02), P<0.001; [underlined: SSB change from 1995-1999]; Low to high (REF, n=765): 1.53 (0.08); Consistent low (n=39,279): 0.75 (0.01),; P<0.001; Consistent high (n=2340): 0.81 (0.05),; P<0.001; High to low (n=1107): 0.05 (0.07), P<0.001; Other (n=8112): 0.77 (0.02), P<0.001; [underlined: Weight (kg)], Mean (SE); Fruit punch change from 1991-1995; Increased intake (≤1/wk to ≥1/d): 3.69 kg; Decreased intake (≥1/d to ≤1/wk): 2.43 kg; P<0.001 | Model adjustments:; - TEI: no; - Key confounders: sex, age, anthropometry at baseline, physical activity, diet quality (cereal fiber intake, total fat intake), smoking; - Other: Postmenopausal hormone use, oral contraceptive use; Limitations:; - Did not account for key confounders: race and/or ethnicity, socioeconomic position; - Attrition 56% without information on non-completers; Weight and height self-reported; No preregistered data analysis plan; Funding:; NIH; European Association for the Study of Diabetes/American Diabetes Association; German Academic Exchange Service (DAAD)
Siqueira, 2023^167^; PCS, ELSA-Brazil cohort, Brazil; Analytic N=4,710; Included in meta-analysis: no; Study purpose: To estimate the association between consumption of sugar-sweetened soft drinks and unsweetened fruit juice with metabolic syndrome and its components in participants of the Brazilian Longitudinal Adult Health Study (ELSABrasil) after 4 years of follow-up; Participant characteristics at baseline: adults, older adults; - Age: Mean (SD): 50 (8.5)y; - Female: 59%; - Race/ethnicity: 51% White; 49% Non-white; - SEP: Education: 53% college, 37% secondary, 10% elementary; Income per capita ($): 876; - Anthropometry: BMI, mean (SD): 24.9 (3.8) kg/m2; - Physical activity: Weak (no exercise): 76%; Moderate (>3days of 20 min high intesity exercise or >5 days 30 min moderate intensity): 16%; Strong (1,500 MET-min/wk high intesity or 7 days of any combination of high and moderate reaching 3,000 METS-min/wk): 8%; - Smoking: Non-smokers: 62%; Former: 24%; Current: 14%; - Alcohol intake: NR; - Diet quality: Mean intake, g/d:; Fruit: 591; Vegetables: 214; Processed meats: 19.8 Unprocessed meats: 148; Fish and seafood: 57.8; Milk and dairy products: 336 (mL/day); Whole grains: 59.5; - TEI: mean 2,944 kcal/d; - Study beverage intake at baseline: SSB consumption servings/d:; <0.1: 64%; ≥0.1-<0.4: 20.5%; ≥0.4-<1: 9.7%; ≥1: 5.7%; Included: active/retired civil servants, ages 35-74y, living in NE, south, and SE regions of Brazil; Excluded: prevalent metabolic syndrome at baseline, prevalence of high WC at baseline (n=8316); history of cardiovascular events and cancer at baseline (n-429), reported intake of diet soda (n=1249), implausible calorie intake (<500 and ≥6000 kcal/d) (n=77), history of bariatric surgery (n=15), missing data on main exposures or outcomes at baseline or in second evaluation (n=309) | Exposure: sugar-sweetened carbonated beverages; Comparator: Categorical, by daily SSB intake: < 0.1 serving/d, ≥0.1 to < 0.4 serving/day, ≥0.4 to < 1 serving/day, and ≥1 servings/day; Assessment methods and timing:; Validated 114-item semi-quantitative FFQ; assessed habitual consumption over last 12 months; mean intake calculated from frequency of servings consumed daily (1 serving = 250mL); Baseline (2008-2010); Outcomes and assessment methods:; Height and weight: valid measure by study staff. BMI calculated from height and weight. WC measured with measuring tape around midpoint between the lower edge of the ribs and the iliac crest. High WC defined as ≥92 cm (men) and ≥86 cm (women).; Baseline, Follow-up (2012-2014) | [underlined: Risk of high WC]: relative risk (95% CI), poisson regression; Baseline SSB intake:; <0.1 serving/d: REF; 0.1-<0.4/d: 1.09 (0.96–1.24); 0.4-<1/d: 1.21 (1.02–1.42); >1/d: 1.15 (0.92–1.44) | Model adjustments:; - TEI: yes and no; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position (per capita income), anthropometry at baseline (WC variation between evaluations), physical activity, diet quality (fruits, vegetables, whole grains, milk and dairy products, fish and seafood, unprocessed meats, processed meats), smoking; - Other: Alcohol; Limitations:; - Did not account for key confounders:; - Start of follow-up and exposure do not coincide; Exposure data only measured at baseline; No preregistered data analysis plan; Baseline demographics only available for full sample size (n=6124) and may differ from sample assessed for WC (n=4710); Funding:; Brazilian Ministry of Health (Department of Science and Technology), Ministry of Science, Technology and Innovation, National Council for Scientific and Technological Development
Smith, 2015^168^; PCS, Nurses’ Health Study (NHS); Nurses’ Health; Study II (NHS II); Health Professionals Follow-up Study (HPFS), U.S.; Analytic N=117,992; NHS: 48,449; NHS II: 48,071; HPFS: 21,472; Included in meta-analysis: yes; Study purpose: To evaluate and compare different methodological approaches for investigating diet, physical activity, and long-term weight gain.; Participant characteristics at baseline: Adults; - Age: Mean (SD), Range; NHS: 49 (6), 40-65y; NHS II: 38 (4) 29-46y; HPFS: 47 (6), 40-75y; - Female: NHS & NHS II: 100%; HPFS: 0%; - Race/ethnicity: Primarily Caucasian; - SEP: Occupation: 100% health professionals; - Anthropometry: BMI, kg/m^2^ Mean (SD); NHS: 23.7(1.4), NHS II: 23.0(2.4), HPFS: 24.7(1.1); Weight, lb Mean (SD):; NHS: 141 (9), NHS II: 138 (17), HPFS: 175 (10); - Physical activity: MET hr/wk; NHS: 14.9 (10), NHS II: 21.6 (23), HPFS: 20.5 (14); - Smoking: NR; - Alcohol intake: NR; - Diet quality: Mean (SD), svg/d, NHS, NHS II, HPFS; Fruits: 1.7(0.6), 1.2(0.8), 1.4(0.6); Vegetables: 3.9(1.0), 3.5(1.8), 3.3(0.9); - TEI: NR; - Study beverage intake at baseline: SSB Mean (SD), svg/d; NHS: 0.2 (0.2), NHS II: 0.3 (0.6), HPFS: 0.3 (0.3); Exclude: death prior to analysis baseline; obesity or chronic disease at baseline; implausible energy intake; missing diet, physical activity, or weight data; pregnancy; data starting at age 65y or 6y prior to diagnosis of chronic disease | Exposure: SSB: Coke, Pepsi, or other cola (1 glass, bottle, or can); Comparator: Continuous intake, svg/d; Assessment methods and timing:; Validated FFQ assessing average intake over previous year; measured frequency of servings categorically, which were converted to continuous svg/d using midpoint value of each category; Baseline and every 4y for 16y (NHS II) or 24y (NHS, HPFS); Outcomes and assessment methods:; Self-reported weight and height Weight measured at baseline and every 2y for 16y (NHS II) or 24y (NHS & HPFS) | Weight change over 24y (NHS, HPFS) or 16y (NHS II) follow up by 4y increment, β (95% CI), p-value; [underlined: Baseline] (SSB intake at start of 4y increment and weight change over subsequent 4y); [underlined: Change] (SSB intake change and weight change over same 4y increment); [underlined: Lagged] (SSB intake change over 4y increment and weight change over subsequent 4y increment); Pooled (all cohorts combined); [underlined: Baseline]: 0.01 (−0.08, 0.11), p = 0.81; [underlined: Change]: 0.99 (0.82, 1.16), p < 0.001; [underlined: Lagged]: 0.06 (−0.10, 0.21), p = 0.48; [underlined: Baseline analysis by cohort]; NHS: −0.07 (−0.18, 0.04), p = 0.24; NHS II: −0.01 (−0.09, 0.08), p = 0.87; HPFS: 0.11 (−0.02, 0.24), p = 0.09; [underlined: Change analysis by cohort]; NHS: 1.02 (0.82, 1.21), p < 0.0001; NHS II: 1.11 (0.95, 1.27), p < 0.0001; HPFS: 0.82 (0.62, 1.02), p < 0.0001; [underlined: Lagged analysis by cohort]; NHS: 0.18 (−0.04, 0.40), p = 0.10; NHS II: −0.08 (−0.24, 0.09), p = 0.39; HPFS: 0.09 (−0.14, 0.32), p = 0.43 | Model adjustments:; - TEI: no; - Key confounders: Sex, age, anthropometry at baseline (BMI at start of each 4y period), physical activity, smoking, and diet quality (fruits, vegetables, whole grains, nuts, dairy, potato chips, potatoes, refined grains, 100% fruit juice, diet soda, sweets or desserts, processed meats, unprocessed red meats, trans fat, fried foods); - Other: Sleep duration, alcohol use, time spent watching TV; Limitations:; - Did not account for key confounders: Race and/or ethnicity, SEP (though all were health professionals); - No information on noncompleters; No preregistered data analysis plan; Funding:; Canadian Institutes of Health Research; NHLBI; NIH
Stern, 2017^169^; PCS, Mexican Teachers’ Cohort, Mexico; Analytic N=11,218; Included in meta-analysis: yes; Study purpose: To evaluate 2-year changes in soda consumption, weight, and waist circumference; Participant characteristics at baseline: Adult women; - Age: 43.3 (5.2)y; Range 25-64; - Female: 100%; - Race/ethnicity: 100% Hispanic; - SEP: NR; - Anthropometry: BMI 27.2 (4.4) kg/m2; 42% Overweight, 23% Obesity; - Physical activity: High 34%, Medium 37%, Low 29%; - Smoking: Never 81%, Current 8%; - Alcohol intake: NR; - Diet quality: Svg/wk; Vegetable: 24.6 (17.2); Fruit: 19.3 (15.0); - TEI: 1756 (614) kcal/d; - Study beverage intake at baseline: Sugar-sweetened soda: 0.4 (0.5) svg/d; Included: Female teachers age 25y or older at baseline; completion of baseline and follow-up questionnaire; Excluded: diabetes, cancer, or heart disease at baseline (n = 1481); age ≥65y; inadequate dietary information in either 2006 or 2008 (energy intake < 500 or > 3500 kcal/day, response to ≤ 70 items on the dietary questionnaire, or missing cereal section); missing information on soda consumption in either 2006 or 2008; missing height or weight data | Exposure: Sugar-sweetened soda; Comparator: Continuous intake; Categorical intake [Decreased (<-1 svg/wk, No change (−1 to +1 svg/wk), Increased (>1 svg/wk)]; Assessment methods and timing:; Semi-quantitative FFQ; represents intake over previous year; validated; Baseline, 2y; Outcomes and assessment methods:; Height (in cm) and weight (in kg) were self-reported; Waist circumference (WC, in cm) was self-reported; participants were provided a plastic measuring tape and instructions to assess their WC; Baseline, 2y | [underlined: WC, cm], change from 2006–2008, linear regression, β (95% CI); Per 1 svg/d increase: 0.9 (0.5, 1.4), P<0.001; [underlined: Per change in svg/wk]:; - No change (−1 to +1, n=5350): Ref; - Decreased (<1, n=2538): −0.5 (−0.9, −0.1); - Increased (>1, n=1406): 0.3 (0.1, 0.6); [underlined: Per 1 svg/d increase, stratified by age]; Baseline age ≥43y: 1.0 (0.4, 1.7); Baseline age<43y: 0.9 (0.2, 1.5); P for heterogeneity: 0.67; [underlined: Per 1 svg/d increase, stratified by BMI:]; Obesity (≥30 kg/m2): 1.2 (0.3, 2.2); Overweight (25-29.9 kg/m2): 1.1 (0.4, 1.8); Normal (<25 kg/m2): 0.6 (−0.2, 1.4); P for heterogeneity: 0.54; [underlined: Weight, kg], Change from 2006–2008, Linear regression, β (95% CI); [underlined: Per 1 svg/d increase]: 1.0 (0.7, 1.2), P<0.001; Per change in svg/wk:; - No change (−1 to +1, n=6409): Ref; - Decreased (<1, n=3075): −0.4 (−0.6, −0.2); - Increased (>1, n=1734): 0.3 (0.2, 0.5); Per 1 svg/d increase, stratified by age:; Baseline age ≥43y: 1.2 (0.8, 1.5); Baseline age<43y: 0.8 (0.4, 1.1); P for heterogeneity: 0.05; [underlined: Per 1 svg/d increase, stratified by BMI]:; Obesity (≥30 kg/m2): 1.5 (1.0, 2.0); Overweight (25-29.9 kg/m2): 1.0 (0.6, 1.3); Normal (<25 kg/m2): 0.6 (0.3, 1.0); P for heterogeneity: 0.003 | Model adjustments:; - TEI: no; - Key confounders: sex, age, race and/or ethnicity, anthropometry at baseline, physical activity, smoking, diet quality (fruit, vegetables, red meat, dairy, yogurt, fruit, vegetables, nuts, white bread, flour tortillas, corn tortillas, orange or grapefruit juice, and homemade sweetened beverages); - Other: Sugar-free soda consumption, state of residency, oral contraceptive use, menopausal status, postmenopausal hormone therapy use; Limitations:; - Did not account for key confounders: SEP; - Attrition 60% without information on non-completers, Weight, height, and waist circumference self-reported, No preregistered data analysis plan; Funding:; AstraZeneca; Bloomberg Philanthropies (National Institute of Public Health in Mexico); Bernard Lown Scholars Program in Cardiovascular Health; American Institute of Cancer Research; Consejo Nacional de Ciencia y Tecnología; NIH
Torquati, 2021^171^; PCS, Australian Longitudinal Study on Women’s Health (ALSWH), Australia; Analytic N=3,300; Included in meta-analysis: yes; Study purpose: To compare the associations between indicators of energy intake and expenditure with excess weight and obesity in women who work full-time in sedentary and less sedentary jobs; Participant characteristics at baseline: Australian women; - Age: Mean (SD): ~33.5 (1.5)y; - Female: 100%; - Race/ethnicity: NR; - SEP: Education: Less sendentary job: 74% university or higher Sedentary job: 48% university or higher; Income percentile: ~30% 25th, ~37% 50th, 32% 75th; Occupation: 100% work full time; - Anthropometry: ~21% with obesity; ~44% with excess weight; - Physical activity: ~710 MET-min/wk; Less sedentary job, median (IQR): 675 (240, 1410) MET min/wk; Sedentary job, median (IQR): 750 (300, 1500) MET min/wk; P=0.048; - Smoking: 17% current, 60% never, 23% former; - Alcohol intake: NR; - Diet quality: sugar intake ~73 g/d; saturated fat intake ~26 g/d; - TEI: kcal/d, mean (CI); Less sedentary job: 1523 (1493, 1547); Sedentary job: 1481 (1452, 1507); p=0.02; - Study beverage intake at baseline: Mean (SD): ~3 (4.8) svg/wk age <31 or >36y at baseline; worked <35 hr/wk at baseline or follow-up; pregnant or recently pregnant at follow-up; missing data on weight and dietary intake at baseline and follow-up; implausible daily energy intake (< 500 or >3500 kcal/d) | Exposure: SSB (non-diet soft drinks, carbonated and non-carbonated drinks, and fruit juice); expressed as svg/wk; Comparator: Categorical (<1, 1-3, >3 svg/wk); Assessment methods and timing:; Validated FFQ; questions asked about weekly SSB consumption over the past year; At baseline; Outcomes and assessment methods:; Weight and height were self-reported and used to calculate BMI. Obesity defined as BMI ≥30 kg/m2; “Excess weight” defined as BMI≥25 kg/m2; At baseline, 3y follow-up | [underlined: Obesity (BMI ≥30 kg/m2) at 3y] follow-up, OR (95% CI); Less sedentary job (n=1203); <1 svg/wk: REF; 1-3 svg/wk: 1.68 (1.07, 2.67); >3 svg/wk: 2.08 (1.42, 3.05); Sedentary job (n=909); <1 svg/wk: REF; 1-3 svg/wk: 1.23 (0.74, 2.05); >3 svg/wk: 1.43 (0.94, 2.21); [underlined: Incidence of obesity at 3y], Poisson regression, IRR (95% CI); Less sedentary job (n=912); <1 svg/wk: REF; 1-3 svg/wk: 1.73 (0.82, 3.65); >3 svg/wk: 2.04 (1.09, 3.80); Sedentary job (n=779); <1 svg/wk: REF; 1-3 svg/wk: 1.35 (0.60, 3.04); >3 svg/wk: 1.00 (0.46, 2.21) | Model adjustments:; - TEI: no; - Key confounders: sex, age, socioeconomic position (education, income), smoking; - Other: number of children, hours worked/wk; Limitations:; - Did not account for key confounders: race and/or ethnicity, anthropometry at baseline, physical activity, diet quality; - Exposure data only measured at baseline; High attrition; height and weight were self-reported; No preregistered data analysis plan; Funding:; No external funding
Tucker, 2015^172^ PCS, U.S.; Analytic N=170; Included in meta-analysis: yes; Study purpose: To examine the association between soft drink consumption and risk of weight gain over 4 years; Participant characteristics at baseline: healthy women; - Age: 41.5 (3.0) y; Range 35-45y; - Female: 100%; - Race/ethnicity: ~90% non-Hispanic white; - SEP: 31% Some college education; 82% Married; - Anthropometry: NR; - Physical activity: 2581611 (823095) activity counts on accelerometer; - Smoking: 100% nonsmokers (inclusion criteria); - Alcohol intake: NR; - Diet quality: NR; - TEI: 2017 (324) kcal/d; - Study beverage intake at baseline: Soft drink intake (12-oz serving): <0.5/wk: 36% Of regular consumers:; 0.5-1/wk: 55.7%, 2-6/wk: 25.3%, ≥7/wk: 19% 40.5% primarily consumed sugar-sweetened soft drinks; 41.8% primarily consumed artificially sweetened soft drinks; Inclusion: nonsmokers, apparently healthy, not pregnant, 35 to 45 years old, and female; Exclusion: NR | Exposure: Sugar-sweetened soft drink intake (12-oz serving); Comparator: Type of soft drink typically consumed (categorical):; None; Artificially sweetened; Mixed (sugar and artificially sweetened); Assessment methods and timing:; Six questions on frequency, type, and size of soft drink intake; represents weekly consumption; At baseline; Outcomes and assessment methods:; Weight measured to the nearest 0.05 kg using computerized electronic scale; all participants used restroom before being weight, wore lightweight nylon swimsuit issue by lab, and were instructed not to eat 3hr prior; At baseline, 4y follow-up | [underlined: Weight, kg], Change per type of soft drink consumed, Multiple regression, β (SE); [underlined: TEI unadj]:; Sugar-sweetened versus No soft drinks: 2.68 (5.14) versus 0.50 (5.05), P<0.05; Sugar-sweetened versus Artificially-sweetened: 2.68 (5.14) versus −0.05 (4.40), P<0.05; Sugar-sweetened versus Mixed soft drinks: 2.68 (5.14) versus 1.22 (5.06), NS; [underlined: TEI adjusted]: “relationship between soft drink consumption and changes in body weight was weakened by 28% and was no longer statistically significant” P=0.051 | Model adjustments:; - TEI: yes and no; - Key confounders: sex, age, anthropometry at baseline, physical activity, smoking; - Other: Menopause status; Limitations:; - Did not account for key confounders: race and/or ethnicity, socioeconomic position, diet quality; - Attrition 25% without information on non-completers, Exposure data collection tool not validated, Exposure only measured at baseline, No preregistered data analysis plan; Funding:; NR
Yi, 2020^174^; PCS, Coronary Artery Risk Development in Young Adults (CARDIA) Study, U.S.; Analytic N=3,070; Included in meta-analysis: no; Study purpose: To determine the relationships of pericardial adipose tissue and visceral adipose tissue volume with added sugar and sugarsweetened beverage intakes; Participant characteristics at baseline: Black and white adults; - Age: Mean (SE): ~24.5 (0.18)y; - Female: 57%; - Race/ethnicity: 53% White; 47% Black; - SEP: 93% high school graduate, 7% non-high school graduate; - Anthropometry: BMI ~24.8 kg/m2; - Physical activity: ~387 physical activity score; - Smoking: 26% current; - Alcohol intake: HEI-2015 score ~59 (average at baseline, 7y and 20y); - Diet quality: HEI-2015 score ~59 (average at baseline, 7y and 20y); - TEI: Mean: 2757 kcal/d (average at baseline, 7y and 20y); - Study beverage intake at baseline: Mean (SE), Range (all svg/d); Q1: 0.57 (0.01), ≤1.05, Q2: 1.51 (0.01), 1.06-1.98; Q3: 2.45 (0.01), 1.99-3.04, Q4: 3.90 (0.02), 3.04-4.88, Q5: 8.00 (0.14), ≥4.89; Exclude: age <18 or >30y at baseline (19851986); energy intake <800 or >8000 kcal/d for men and <600 or >6000 kcal/d for women; prevalent diabetes; missing computed tomography scan | Exposure: SSB (no other description given in article); Comparator: Categorical (quintiles, svg/d), by average AS intake from baseline, 7y and 20y; Assessment methods and timing: CARDIA diet history, which included details on frequency and amounts consumed; At baseline, 7y and 20y follow-up; Outcomes and assessment methods:; Weight and height were measured using standard methods and used to calculate BMI. Visceral adipose tissue (VAT) and subcutaneous adipose tissue (SAT) were measured by computed tomography.; At 25y follow-up | [underlined: Back-transformed VAT (mL) at 25y] follow-up based on quintiles of averaged years 0, 7, and 20 of SSB intake (svg/d), linear regression, Mean (SE); Q1: 110.1 (1.03); Q2: 113.0 (1.03); Q3: 116.7 (1.03); Q4: 118.3 (1.03); Q5: 118.3 (1.03); p-trend=0.004; [underlined: Back-transformed SAT (mL) at 25y] follow-up based on quintiles of averaged years 0, 7, and 20 of SSB intake (svg/d), linear regression, Mean (SE); Q1: 263.5 (1.02); Q2: 270.8 (1.02); Q3: 266.6 (1.02); Q4: 261.1 (1.02); Q5: 269.5 (1.02); p-trend=0.68; [underlined: BMI (kg/m2) at 25y] follow-up based on quintiles of averaged years 0, 7, and 20 of SSB intake (svg/d), linear regression, Mean (SE); Q1: 31.7 (0.45); Q2: 31.7 (0.44); Q3: 32.1 (0.44); Q4: 31.9 (0.44); Q5: 32.6 (0.44); p-trend=0.04 | Model adjustments:; - TEI: yes; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position (education), anthropometry at baseline, physical activity, smoking, diet quality (saturated fat, protein, fiber, folic acid, potassium, vitamin C, calcium, vitamin D, iron, magnesium); - Other: field center; current drinking; diabetes at 25y followup; Limitations:; - High attrition with no information on non-completers; No preregistered data analysis plan; Funding:; NHLBI

a Abbreviations: β: regression coefficient; BMI: body mass index; CI: confidence interval; CDC: Centers for Disease Control; d: day(s); EPIC: European Prospective Investigations into Cancer and Nutrition Study; FFQ: food frequency questionnaire; g: gram(s); HAZ: height-for-age z-score; hr: hour; HR: hazard ratio; kcal: kilocalorie(s); kg: kilogram(s); L: liter; LNCSB: low- and no-calorie sweetened beverage(s); m: meter(s); mg: milligram(s); min: minute(s); mL: milliliter(s); N/A: not applicable; NIDDK: National Institute of Diabetes and Digestive and Kidney Diseases; NHS: Nurses’ Health Study; NIH: National Institutes of Health; NR: not reported; NS: not significant; OR: odds ratio; PCS: prospective cohort study; REF: reference group; RCT: Randomized controlled trial; SD: standard deviation; SE: standard error; SEP: Socioeconomic position; SSB: sugar-sweetened beverage(s); svg: serving(s); TEI: total energy intake; USDA: United States Department of Agriculture; WHZ: weight-for-height z-score; wk: week(s); y: year(s)

Table 16 Risk of bias for randomized controlled trials examining sugar-sweetened beverage consumption and body composition and risk of obesity in adults^a^

Article | Randomization | Deviations from intended interventions (effect of assignment) or (per-protocol) | Missing outcome data | Outcome measurement | Selection of the reported result | Overall risk of bias
Campos, 2015 ^122^ | SOME CONCERNS | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Ebbeling, 2020 ^131^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Hernández-Cordero, 2015 ^142^ | LOW | LOW | LOW | LOW | LOW | LOW
Higgins, 2019 ^143^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Kendig, 2023 ^149^ | SOME CONCERNS | SOME CONCERNS | HIGH | LOW | SOME CONCERNS | SOME CONCERNS
Maersk, 2012 ^154^ | HIGH | SOME CONCERNS | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Tate, 2012 ^170^ | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Vazquez-Duran, 2016 ^173^ | LOW | LOW | LOW | LOW | LOW | LOW

a Possible ratings of low, some concerns, or high determined using the “Cochrane Risk-of-bias 2.0” (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2019 version)” ( Sterne JAC, Savović J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ 2019; 366: l4898. doi:10.1136/bmj.l4898.31462531 )

Table 17 Risk of bias for observational studies examining sugar-sweetened beverage consumption and body composition and risk of obesity in adults^a^

Article | Confounding | Selection of participants | Classification of interventions | Deviations from intended interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Acero, 2020 ^112^ | VERY HIGH | LOW | SOME CONCERNS | LOW | HIGH | LOW | SOME CONCERNS | VERY HIGH
Appelhans, 2017 ^113^ | HIGH | LOW | SOME CONCERNS | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Auerbach, 2018 ^114^ | LOW | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Barone-Gibbs, 2012 ^115^ | HIGH | LOW | SOME CONCERNS | LOW | LOW | SOME CONCERNS | SOME CONCERNS | HIGH
Barrio-Lopez, 2013 ^116^ | HIGH | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | HIGH
Bes-Rastrollo, 2008 ^118^ | HIGH | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Bes-Rastrollo, 2006 ^117^ | HIGH | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Boggs, 2013 ^119^ | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | HIGH
Bundrick, 2014 ^120^ | HIGH | SOME CONCERNS | SOME CONCERNS | LOW | HIGH | LOW | HIGH | HIGH
Buso, 2022 ^121^ | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Carroll, 2018 ^123^ | HIGH | SOME CONCERNS | SOME CONCERNS | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Castellana, 2020 ^124^ | HIGH | HIGH | SOME CONCERNS | LOW | HIGH | LOW | HIGH | VERY HIGH
Chen, 2009 ^125^ | LOW | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Chen, 2010 ^126^ | HIGH | LOW | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | HIGH
Cleland, 2018 ^127^ | HIGH | VERY HIGH | SOME CONCERNS | LOW | HIGH | SOME CONCERNS | SOME CONCERNS | VERY HIGH
Dhingra, 2007 ^128^ | HIGH | VERY HIGH | SOME CONCERNS | LOW | HIGH | LOW | SOME CONCERNS | VERY HIGH
Drapeau, 2004 ^129^ | HIGH | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Duffey, 2010 ^130^ | HIGH | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Ferreira-Pego, 2016 ^132^ | HIGH | SOME CONCERNS | SOME CONCERNS | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Fowler, 2015 ^133^ | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Fowler, 2008 ^134^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | LOW | LOW | HIGH | HIGH
French, 2012 ^29^ | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | HIGH
Funtikova, 2015 ^135^ | SOME CONCERNS | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Garduño-Alanís, 2020 ^136^ | SOME CONCERNS | LOW | SOME CONCERNS | LOW | HIGH | SOME CONCERNS | SOME CONCERNS | HIGH
Gearon, 2018 ^137^ | HIGH | SOME CONCERNS | SOME CONCERNS | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Gibbs, 2020 ^138^ | HIGH | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Gonzalez-Morales, 2020 ^139^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Halkjaer, 2009 ^140^ | HIGH | SOME CONCERNS | LOW | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | HIGH
Hasselbalch, 2010 ^141^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Hosseinpour-Niazi, 2021 ^144^ | SOME CONCERNS | LOW | HIGH | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Inoue, 2010 ^145^ | HIGH | HIGH | SOME CONCERNS | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Kaikkonen, 2015 ^146^ | HIGH | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Kang, 2017 ^147^ | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Kärkkäinen, 2018 ^148^ | HIGH | HIGH | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | HIGH
Konieczna, 2019 ^150^ | LOW | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Kvaavik, 2005 ^151^ | HIGH | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | HIGH
Larson, 2018 ^50^ | HIGH | LOW | LOW | LOW | HIGH | SOME CONCERNS | SOME CONCERNS | HIGH
Lim, 2021 ^152^ | LOW | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Ma, 2016 ^153^ | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | HIGH
Moshtaghian, 2021 ^155^ | HIGH | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Mozaffarian, 2011 ^156^ | HIGH | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | HIGH
Mullie, 2017 ^157^ | HIGH | LOW | SOME CONCERNS | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Nooyens, 2005 ^158^ | HIGH | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Odegaard, 2010 ^159^ | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | HIGH
Olsen, 2016 ^160^ | HIGH | SOME CONCERNS | SOME CONCERNS | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Palmer, 2008 ^161^ | LOW | LOW | SOME CONCERNS | LOW | HIGH | SOME CONCERNS | SOME CONCERNS | HIGH
Pan, 2013 ^175^ | HIGH | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | HIGH
Partridge, 2016 ^162^ | HIGH | HIGH | SOME CONCERNS | LOW | LOW | SOME CONCERNS | SOME CONCERNS | HIGH
Qi, 2012 ^163^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | HIGH
Romaguera, 2011 ^164^ | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Schulz, 2002 ^165^ | HIGH | SOME CONCERNS | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | HIGH
Schulze, 2004 ^166^ | HIGH | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | HIGH
Siqueira, 2023 ^167^ | LOW | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Smith, 2015 ^168^ | SOME CONCERNS | LOW | SOME CONCERNS | LOW | HIGH | SOME CONCERNS | SOME CONCERNS | HIGH
Stern, 2017 ^169^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | HIGH | SOME CONCERNS | HIGH
Torquati, 2021 ^171^ | HIGH | SOME CONCERNS | LOW | LOW | HIGH | SOME CONCERNS | SOME CONCERNS | HIGH
Tucker, 2015 ^172^ | HIGH | HIGH | SOME CONCERNS | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Yi, 2020 ^174^ | LOW | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH

a Possible ratings of low, some concerns, high, very high, no information, or not applicable were determined using the “Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)” tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602. ) *Low risk of bias except for concerns about uncontrolled confounding.

Table 18 Evidence examining the relationship between SSB consumption during pregnancy and gestational weight gain^a^

Study and Population Characteristics | Intervention or Exposure, Comparator, and Outcome(s) | Results | Confounding and Study Limitations
Figueroa, 2020^176^; PCS, Sub-sample of Massachusetts General Hospital First 1000 Days program, U.S.; Analytic N=111; Participant Characteristics at Baseline: women during pregnancy; - Age: NR; - Female: 100%; - Race/ethnicity: 43% White; 6% Black; 23% Asian or Other; 25% Hispanic; - SEP: 62% employed; 73% gross annual income <$50,000; 60% married; 60% married; - Anthropometry: Pre-pregnancy BMI: 3% underweight, 41% healthy weight, 33% with overweight, 20% with obesity; - Physical activity: NR; - Smoking: NR; - Diet quality: 60% consume fruits/vegetables ≥1x/d; - Parity: NR; - TEI: NR; - Study beverage intake at baseline: 40% consumed SSB ≥1x/d; Excluded from Study or Analysis: dyads with missing data | Exposure: SSB (fruit-flavored drinks, juice from concentrate, punch, soda, sports drinks, sweet tea or coffee drinks, or sweetened milks); Comparator: dichotomous intake (<1x/d versus ≥1x/d); Exposure Assessment Methods and Timing:; “During the past 7 days, on average, how often did you drink 100% fruit juice or a sugar-sweetened beverage?”. Mothers and fathers dichotomized as consuming SSB <1/d or ≥1/d, then categorized as dyads into 4 groups: Healthy concordant (n = 42): mothers and fathers both consume SSB <1/d; Unhealthy concordant (n=18): mothers and fathers both consume SSB ≥1/d; Mother-healthy discordant (n = 28): mothers consume SSB <1/d, but fathers consume SSB ≥1/d; Father-healthy discordant (n = 23): fathers consume SSB <1/d, but mothers consume SSB ≥1/d During first trimester; Outcome Assessment Methods and Timing:; - GWG: difference between measured weight in first trimester and last weight in third trimester. If mother’s weight at either time point was missing from EMR during pregnancy, mothers’ self-reported weight at first survey time point was used (n = 22/111 mothers). Maternal pre-pregnancy weight and height self-reported by mothers and used to calculate pre-pregnancy BMI. Excessive GWG (>9kg) defined according to IOM guidelines; - During first trimester and third trimester (within 14d before birth) | [underlined: Excessive GWG by mother’s SSB][underlined: intake during first trimester], OR (95% CI); <1/d (n = 42, healthy concordant): REF; ≥1/d (n = 18, unhealthy concordant): 0.72 (0.19, 2.66); <1/d (n = 42, healthy concordant): REF; ≥1/d (n = 23, father-healthy discordant): 0.96 (0.25, 3.73) | Model Adjustments:; - TEI: no; - Key confounders: age, anthropometry at baseline, diet quality; - Other: infant gestational age; Limitations:; - Did not account for key confounders: race and/or ethnicity, socioeconomic position, physical activity smoking, parity, diabetes mellitus in the current pregnancy, hypertensive disorders in the current pregnancy; - Exposure data only measured at baseline using single question; No preregistered data analysis plan; Funding:; The Boston Foundation; Massachusetts General Hospital for Children; Harvard Education Program in Cancer Prevention and Control; NIH
Guilloty, 2015^177^; PCS, Puerto Rico Testsite for Exploring Contamination Threats (PROTECT), U.S. (Puerto Rico); Analytic N=160; Participant Characteristics at Baseline:; Puerto Rican individuals during pregnancy; - Age: Mean (SD) = 27.4 (5.3) y; - Female: 100%; - Race/ethnicity: NR; - SEP: Education: 84% > high school, 16%≤ high school ; Income: 40% <$20,000 family annual income (poverty threshold for 2012 in Puerto Rico), 60% ≥$20,000. 14% non-response rate for income reporting.; - Anthropometry: Pre-pregnancy BMI: 6% with underweight, 50% with normal weight, 25% with overweight, 19% with obesity; - Physical activity: NR; - Smoking: NR; - Diet quality: NR; - Parity: NR; - TEI: NR; - Study beverage intake at baseline: Soft drinks <1/day ~87% Fruit drinks <1/day ~52%; Excluded from Study or Analysis: age <18y or >40y; living outside of northern karst region of Puerto Rico; not planning to give birth in one of three participating hospitals; ≥20wk gestation; pregnancy complications; pre-pregnancy use of birth control pills; pregnancy conceived by use of assistive reproductive technology; conditions or complications such as diabetes, hypertension, or heart disease; missing exposure data | Exposure: Soft drinks and fruit drinks; details and serving size NR; Comparator: dichotomous intake (<1/d, ≥1/d); Exposure Assessment Methods and Timing:; Validated, self-administered, semi-quantitative FFQ; represents intake during previous 12mo; Between second and third prenatal visit (20-28wk); Outcome Assessment Methods and Timing:; - GWG calculated from difference between last and initial weight (first prenatal visit at 16-20wk) recorded in medical record. Participants were classified as “inadequate GWG” if weight gain was below, “appropriate GWG” if weight gain was according, and “excessive GWG” if weight gain was above the IOM 2009 guidelines.; - Last prenatal visit before delivery | [underlined: Gestational weight gain], Chi-square difference; Soft Drinks, Total Sample; Excessive GWG: 24.4% <1/d versus 27.3% ≥1/d; Appropriate GWG: 49.6% <1/d versus 54.5% ≥1/d; Inadequate GWG: 25.9% <1/d versus 18.2% ≥1/d; P=0.83; Soft drinks, stratified by pre-pregnancy BMI (Under & Normal weight):; Excessive GWG: 10.8% <1/d versus. 23.1% ≥1/d; Appropriate GWG: 56.8% <1/d versus. 53.8% ≥1/d; Inadequate GWG: 32.4% < 1/d versus. 23.1% ≥1/d; P=0.19; Soft drinks, stratified by pre-pregnancy BMI (With overweight or obesity):; Excessive GWG: 41.0% <1/d versus. 33.3% ≥1/d; Appropriate GWG: 41.0% <1/d versus. 55.6% ≥1/d; Inadequate GWG: 18.0% < 1/d versus. 11.1% ≥1/d; P=0.58; Fruit Drinks, Total Sample; Excessive GWG: 22.0% <1/d versus 30.8% ≥1/d; Appropriate GWG: 55.9% <1/d versus 33.3% ≥1/d; Inadequate GWG: 22.0% <1/d versus 35.9% ≥1/d P=0.047; Fruit drinks, stratified by pre-pregnancy BMI (Under & Normal weight):; Excessive GWG: 6.8% <1/d versus. 22.2% ≥1/d; Appropriate GWG: 64.4% <1/d versus. 40.7% ≥1/d; Inadequate GWG: 28.8% < 1/d versus. 37.0% ≥1/d; P=0.51; Fruit drinks, stratified by pre-pregnancy BMI (With overweight or obesity):; Excessive GWG: 37.3% <1/d versus. 50.0% ≥1/d; Appropriate GWG: 47.5% <1/d versus. 16.7% ≥1/d; Inadequate GWG: 15.3% < 1/d versus. 33.3% ≥1/d; P=0.34 | Model Adjustments:; - TEI: no; - Key confounders: anthropometry at baseline, diabetes mellitus in the current pregnancy (exclusion criteria), hypertensive disorders in the current pregnancy (exclusion criteria); - Other: N/A; Limitations:; - Did not account for key confounders: age, race and/or ethnicity, physical activity, smoking, diet quality, parity; - Exposure not well defined; Exposure data only measured once; Low response rate for completing and returning FFQ, differences in FFQ completers versus. non-completers (completers were younger and with higher education and income); No preregistered data analysis plan; Funding:; Superfund Research for the National Institute of Environmental Health Sciences; RCMI Clinical Research Center; Center for Collaborative Research in Health Disparities; Puerto Rico Clinical and Translational Research Consortium; NIH Institute of Minority Health and Health Disparities
Lai, 2019^178^; PCS, Growing Up in Singapore Towards healthy Outcomes (GUSTO), Singapore; Analytic N=960; Participant Characteristics at Baseline:; Pregnant women in Singapore; - Age: Mean (SD): 30.5 (5.1)y; - Female: 100%; - Race/ethnicity: Ethnicity: 55.3% Chinese, 26.3% Malay, 18.4% Indian; - SEP: Education: 29.5% ≤ Secondary; 36.8% post-secondary; 33.7% University; Monthly Household Income: 14.2% < 1999; 56.9% 2000-5999; 28.9% >6000 (units not indicated, probably Singapore dollars); - Anthropometry: Pre-pregnancy BMI: 12.1% with underweight; 63.1% with normal weight; 17.6% with overweight; 7.2% with obesity; - Physical activity: MET mins/wk, median (IQR): 1040 (329, 2673); - Smoking: 97.8% did not smoke during pregnancy; - Diet quality: Fruit and vegetables, median (IQR): 150 (52.9, 291.5) g/day; Fast food and savoury snacks: 55.5% no intake; Desserts and sweet snacks: 51.6% no intake; - Parity: 31.3% nulliparous; - TEI: Mean (SD): 1868 (598) kcal/d; - Study beverage intake at baseline: 45% no SSB intake; 55% some SSB intake; Excluded from Study or Analysis: women in second or third trimester; not Singapore citizens or permanent residents of Chinese, Malay, or Indian ethnicity; heterogenous parental ethnic background; intention to move outside of Singapore within next 5y; no agreement to donate birth tissues at delivery; receiving chemotherapy or psychotropic drugs; type 1 diabetes; multiple births or IVF treatment; missing data on exposure or outcome | Exposure: SSB (carbonated drinks, fruit juices, cordials, other sweetened beverages); Comparator: Categorical intake, by tertiles, g/d:; Tertile 1: no intake; Tertile 2, median (IQR): 210 (150, 250); Tertile 3, median (IQR): 500 (397, 700); For MSM sub-analyses (24-hr recall data + 3-d food record, n=193), median (IQR); Tertile 1: no intake; Tertile 2: 152.6 (173.3, 202.9) g/day; Tertile 3: 244.9 (234.7, 276.5) g/day; Exposure Assessment Methods and Timing:; Single 24-hr recall (all participants) and one 3-d food diary (n = 193). Main analyses based on 24-hr recall data; subgroup analyses based on 24-hr recall and 3-d food diary using multiple source method (MSM). 26-28wk gestation; Outcome Assessment Methods and Timing:; - Inadequate, adequate, and excessive GWG defined using IOM recommendations in the 2nd and 3rd trimesters according to pre-pregnancy BMI. Pre-pregnancy BMI was based on self-reported weight and height measured by study staff. Rate of weight gain computed with linear mixed-effects model. Inadequate weight gain defined as weight gain rate less than recommended lower limit, and excessive weight gain defined as weight gain rate greater than recommended upper limit. Pre-pregnancy weights were not used in the estimation of weight gain rate to minimize self-reporting bias.; - ≥2 time points between 15 to 35 weeks gestation | [underlined: GWG Status], RRR (95% CI), multinomial logistic regression with adequate GWG as reference (n=231); Inadequate weight gain (n = 114); T1 (no intake): REF; T2: 0.91 (0.51, 1.63), P=0.753; T3: 0.98 (0.56, 1.71), P=0.933; P-trend: 0.897; MSM subgroup analysis (n = 22); T1 (no intake): REF; T2: 0.52 (0.08, 3.43), P=0.500; T3: 0.76 (0.10, 5.51), P=0.785 P-trend: 0.782; Excessive weight gain (n = 615); T1 (no intake): REF; T2: 1.04 (0.71, 1.54), P=0.82; T3: 0.84 (0.58, 1.23), P=0.379; P-trend: 0.419; MSM subgroup analysis (n = 147); T1 (no intake): REF; T2: 0.24 (−0.06, 0.81), P=0.063; T3: 0.39 (0.10, 1.56), P=0.184 P-trend: 0.691 | Model Adjustments:; - TEI: yes; - Key confounders: age, race and/or ethnicity, socioeconomic position (education, household income), anthropometry at baseline, physical activity, smoking, parity, diabetes mellitus in the current pregnancy; - Other: Alcohol consumption; Limitations:; - Did not account for key confounders: diet quality, hypertensive disorders in the current pregnancy; - Start of follow-up and exposure do not coincide (exposure data measured mid-tolate pregnancy); No preregistered data analysis plan; Funding:; Singapore National Research Foundation; Singapore Institute for Clinical Sciences, Agency for Science Technology and Research (A*STAR), Nestec, National Institute for Health Research, European Union’s Seventh Framework Programme
Olaffsdottir, 2006^179^; PCS, Iceland; Analytic N=406; Participant Characteristics at Baseline:; Pregnant, Caucasian Icelandic women; - Age: ~28y; - Female: 100%; - Race/ethnicity: All Caucasian; - SEP: NR; - Anthropometry: 39% with overweight or obesity at beginning of pregnancy Baseline weight, Mean (SD) Suboptimal GWG: 66 (14) kg Optimal GWG: 69 (13) kg Excessive GWG: 74 (11) kg P <0.001; - Physical activity: NR; - Smoking: NR; - Diet quality: ~14% of total energy intake from added sugars.; - Parity: NR; - TEI: NR; Excluded from Study or Analysis: not Caucasian, miscarriage or stillbirth, pregnant with twins or triplets, preterm birth, missing data (including FFQ and lifestyle questionnaires) | Exposure: Energy-providing drinks (total calorie-containing drinks, juices, and soft drinks) during early or late pregnancy compared with usual intake before pregnancy; Comparator: Different intake of energyproviding drinks; Assessment Methods and Timing: Lifestyle questionnaire with multiple choice questions on changes in eating patterns in early and late pregnancy compared with usual intake before pregnancy (yes/no answer) 11-15 wks gestation (early pregnancy), 34-37 wks gestation (late pregnancy); - [underlined: Study beverage intake at baseline:] NR; Outcome Assessment Methods and Timing:; - GWG estimated by subtracting weight at first visit at 11–15 weeks gestation from last weight measurement before delivery. GWG was divided into groups of suboptimal, optimal and excessive weight gain, according to recommendations based on Icelandic studies on maternal weight gain. Optimal weight gain: 12.1–18.0 kg for prepregnantly normal-weight women and 7.1–12.0 kg for overweight women.; - 11–15 weeks gestation; last weight measurement before delivery | [underlined: GWG when drinking energy-providing drinks during pregnancy] NS (results not shown) | Model Adjustments:; - TEI: no; - Key confounders: age, race and/or ethnicity, socioeconomic position, anthropometry at baseline, smoking, physical activity, parity; - Other: Gestational length, fetal sex; Limitations:; - Did not account for key confounders: diet quality, diabetes mellitus in the current pregnancy, hypertensive disorders in the current pregnancy; - Exposure not well defined; No preregistered data analysis plan; Funding:; Icelandic Research Council; University of Iceland Research Fund
Renault, 2015^180^; PCS, Secondary analysis of TOP (Treatment of Obese Pregnant Women) trial, Denmark; Analytic N=365; Participant Characteristics at Baseline:; women during pregnancy; - Age: 31 (4)y; - Female: 100%; - Race/ethnicity: NR; - SEP: NR; - Anthropometry: Pre-pregnancy BMI ~33.8 kg/m2; - Physical activity: NR; - Smoking: 0.07; - Diet quality: added sugar ~7% of energy intake; saturated fat ~13% of energy intake; - Parity: 0.44; - TEI: ~1912 kcal/d; Excluded from Study or Analysis: pre-pregnancy BMI <30 kg/m2; gestational age ≥16wk; age ≤18y; disease limiting physical activity; not normal, singleton pregnancy | Exposure: Sugar-sweetened carbonated soft drinks; Comparator: categorical intake (0, <1/day, ≥1/day); Exposure Assessment Methods and Timing:; Validated FFQ assessing intake over previous 4wk; At baseline (11-14wk gestation); - [underlined: Study beverage intake at baseline:] Daily SSB intake: 36% none, 58% <1/d, 6% ≥1/d; Outcome Assessment Methods and Timing:; - GWG calculated as difference between self-reported pre-pregnancy weight and measured weight prior to delivery; excessive GWG (>9kg) defined according to IOM guidelines; - At baseline (11-14wk gestation) and endpoint (36-37wk gestation) | [underlined: Excessive GWG by baseline intake], RR; (95% CI), linear regression; No SSB: REF; <1/d: 0.79 (0.65, 0.96); ≥1/d: 0.62 (0.36, 1.05); P-trend=0.001 | Model Adjustments:; - TEI: yes; - Key confounders: age, anthropometry at baseline, smoking, parity; - Other: intervention group; Limitations:; - Did not account for key confounders: race and/or ethnicity, socioeconomic position, physical activity, diet quality, diabetes mellitus in the current pregnancy, hypertensive disorders in the current pregnancy; - Only baseline exposure data used in analysis; Outcome based on self-reported pre-pregnancy weight; Funding:; Sygekassernes Helsefond; Brødrene Hartmann Fonden; Danish Council for Strategic Research
Samano, 2022^181^; PCS, Mexico; Analytic N=530; Participant Characteristics at Baseline:; adolescents during pregnancy; - Age: 15.8 (1.3)y; - Female: 100%; - Race/ethnicity: NR but likely majority Hispanic; - SEP: 75% elementary education, 89% dropouts of school; mostly low or very low SES, 89% were homemakers; - Anthropometry: NR; - Physical activity: NR; - Smoking: NR; - Diet quality: 72% consumed insufficient fruits (<3-4 svg/d) , 93% consumed insufficient vegetables (≤3 svg/d); - Parity: All nulliparous/primigravida; - TEI: 2022 (657) kcal/d; Excluded from Study or Analysis: age <11 or >19y; not primigravida with single pregnancy; chronic disease diagnosis; adolescents with drug addictions, vegans or vegetarians, and those who had a newborn with congenital malformations, stillbirth | Exposure: Sugar-sweetened beverages; Comparator: Dichotomous intake (adequate versus excessive) Adequate was defined when the number of servings was met according to the recommed intake of 0 servings of SSB. Excessive was defined when participants drank more than the recommended intake of 0 servings of SSB.; Exposure Assessment Methods and Timing:; Single semi-quantitative FFQ measuring intake of 9 food groups; assessing frequency of intake during the last trimesters. 3 24-h recalls were recorded to assess TEI and macronutrient intake. 2nd or 3rd trimester; - [underlined: Study beverage intake at baseline:] 68% consumed excessive SSB (>0 svg/d); median (25th, 75th percentile): 2 (0.5, 11) svg/d; Outcome Assessment Methods and Timing:; - Gestational weight gain (GWG) calculated by subtracting self-reported initial pre-pregnancy weight from measured final gestational weight. Adequacy of GWG was based on IOM recommendations and was categorized as inadequate/insufficient (<90%), adequate (90 to <125%), and excessive (≥125%).; - 1-2wk before delivery | [underlined: GWG adequacy], unadjusted Chi-square Adequate SSB (0 svg/d, n = 171): 33.3% insufficient GWG, 33.3% excessive GWG Excessive SSB (>0 svg/d, n = 359): 39.3% insufficient GWG, 38.2% excessive GWG; P=0.030; [underlined: GWG adequacy by SSB consumption],; Poisson regression, Prevalence Ratio; (95% CI); Insufficient GWG; Adequate SSB (0 svg/d): REF; Excessive SSB (>0 svg/d): 1.19 (0.87, 1.62); Excessive GWG:; Adequate SSB(0 svg/d): REF; Excessive SSB (>0 svg/d): 1.14 (0.84, 1.56) | Model Adjustments:; - TEI: no; - Key confounders: 68% consumed excessive SSB (>0 svg/d); median (25th, 75th percentile): 2 (0.5, 11) svg/d; - Other: gynecological age, antenatal care; Limitations:; - Did not account for key confounders: race and/or ethnicity, physical activity, diet quality, smoking, diabetes mellitus in the current pregnancy, hypertensive disorders in the current pregnancy; - Exposure data only measured at baseline; No information on non-completers; Pre-pregnancy weight was self-reported; No preregistered data analysis plan; Funding:; Instituto Nacional de Perinatología; CONACyT
Stuebe, 2009^182^; PCS, Project Viva, U.S.; Analytic N=1,388; Participant Characteristics at Baseline:; women during pregnancy; - Age: 26% <30y; 45% 30-<35y; 29% ≥35y; - Female: 100%; - Race/ethnicity: 76% White; 10% Black; 5% Asian; 3% Other; 5% Hispanic; - SEP: NR; - Anthropometry: 73% BMI <26 kg/m2; 12% BMI 26-29; 12% BMI >29; - Physical activity: walking 34 min/d; - Smoking: 11% current, 23% former, 67% never; - Diet quality: 5.9 svg/d fruits and vegetables; 1.26 svg/d whole grains; 0.11 svg/d fried foods; - Parity: 51% nulliparous, 35% primiparous, 14% multiparous; - TEI: ~2100 kcal/d; Excluded from Study or Analysis: not fluent in English; ≥22wk gestation at study entry; not singleton pregnancy; missing information on diet and pre-pregnancy BMI and gestational weight gain, missing data on covariates | Exposure: SSB intake (details NR); Comparator: continuous intake (svg/d); Exposure Assessment Methods and Timing:; Validated FFQ; questionnaire during first trimester covered diet since last menstrual period, and questionnaire during second trimester covered previous 3mo. Mean of first and second trimester intake used in analysis; During first trimester (mean 11.7wk gestation) and second trimester (mean 29.2wk gestation); - Study beverage intake at baseline: ~0.37 svg/d; Outcome Assessment Methods and Timing:; - GWG calculated as difference between self-reported pre-pregnancy weight and last recorded weight prior to delivery; excessive GWG defined according to IOM guidelines (BMI<19.8 should gain 12.5-18 kg, BMI 19.8-26 should gain 11.5-16 kg, BMI 26-29 should gain 7-11.5 kg, BMI >29 should gain 6.8-11.5kg); - Last weight recorded prior to delivery (after 34 wk) | [underlined: Excessive GWG by mean of first and second trimester SSB intake], OR (95% CI); 0.87 (0.72, 1.05) | Model Adjustments:; - TEI: yes and no; - Key confounders: age, race and/or ethnicity, socioeconomic position (employment, maternal education, household income), anthropometry at baseline, smoking, parity, physical activity (work-related); - Other: gestational age at delivery; nausea in first trimester of pregnancy; Edinburgh depression score; dietary cravings,; Limitations:; - Did not account for key confounders: diet quality, diabetes mellitus in the current pregnancy, hypertensive disorders in the current pregnancy; - Excessive GWG based on self-reported pre-pregnancy weight; No preregistered data analysis plan; Funding:; NIH; Harvard Medical School; Harvard Pilgrim Health Care Foundation

a Abbreviations: BMI: body mass index; CI: confidence interval; d: day(s); EMR: electronic medical record; FFQ: food frequency questionnaire; g: gram(s); GWG: gestational weight gain; IOM: Institute of Medicine; kcal: kilocalorie(s); kg: kilogram(s); LNCSB: low- and no-calorie sweetened beverage(s); m: meter(s); mg: milligram(s); min: minute(s); mL: milliliter(s); N/A: not applicable; NIH: National Institutes of Health; NR: not reported; NS: not significant; OR: odds ratio; PCS: prospective cohort study; RCMI: Research Centers in Minority Institutions; REF: reference group; RCT: Randomized controlled trial; SD: standard deviation; SE: standard error; SEP: Socioeconomic position; SSB: sugar-sweetened beverage(s); svg: serving(s); TEI: total energy intake; wk: week(s); y: year(s)

Table 19 Evidence examining the relationship between SSB consumption during postpartum and postpartum weight change^a^

Study and Population Characteristics | Intervention or Exposure, Comparator, and Outcome(s) | Results | Confounding and Study Limitations
Alderete, 2020^183^; PCS, Southern California Mother’s Milk Study, U.S.; Analytic N=99; Participant Characteristics at Baseline:; Postpartum women; - Age: Mean (SD): 29.4 (6.5)y; - Female: 100%; - Race/ethnicity: 100% self-identified as Hispanic (inclusion criteria); - SEP: NR; - Anthropometry: Weight, kg, mean (SD): 73.1 (13.1); BMI, kg/m2, mean (SD): 29.8 (4.8); pre-pregnancy: 29% healthy weight, 38% overweight, and 32% with obesity; - Physical activity: NR; - Smoking: All nonsmokers or <1 cigarette/wk (part of exclusion criteria); - Diet quality: No summary metric; data on mean dietary intake available in Table 2; - Parity: NR; - TEI: Kcal/day, mean (SD): 1666 (375); Excluded from Study or Analysis: <18y at time of delivery; preterm or multiple birth; >1mo postpartum; no intention to breastfeed for ≥3mo postpartum, taking medications or had any medical conditions that could affect metabolism, nutritional status, or physical or mental health; current use of tobacco (i.e., >1 cigarette/wk) or other recreational drugs; clinical diagnosis of fetal abnormalities; Current article, excluded: dietary data unavailable at 1- and 6-months postpartum (n=114); dietary sugar variables (i.e., sucrose, mannitol, soft drinks, sweets) >2 SD above mean (n=4); weight loss >11 SD above the mean (n=1) | Exposure: 1) Sweetened soft drinks; 2) sugary beverages excluding juice (sweetened soft drinks + sweetened fruit drinks + sweetened tea + sweetened coffee + sweetened coffee substitutes + sweetened water + nondairy-based sweetened meal replacement/supplement + ready-to-drink flavored milk + sweetened flavored milk beverage powder); 3) Sugary beverages excluding juice and dairy (sugary beverages excluding juice − (ready-to-drink flavored milk + sweetened flavored milk beverage powder); 8oz svg/d (236.6 mL/d); Comparator: Different intake of SSB, continuous (half a serving per day); Exposure Assessment Methods and Timing:; Two nonconsecutive 24-h dietary recalls (unclear if validated) conducted on 1 weekday and 1 weekend day using the multipass method. Data at all 4 time points were averaged to represent mean dietary intake.; 1 and 6 mo postpartum; - [underlined: Study beverage intake at baseline:] 8-ounce servings/day, mean (SD) Sweet soft drinks: 0.4 (0.5); Sugary beverages excluding juice: 0.9 (0.7); Sugary beverages excluding juice and dairy: 0.8 (0.7); Outcome Assessment Methods and Timing:; - Weight: valid measure by study staff.; - 1 and 6 mo postpartum | [underlined: Postpartum weight change from 1 to 6 months per half 8-ounce serving per day increase in beverage type], kg, β (95% CI), multiple linear regression; Sweet soft drinks: 1.46 (0.57, 2.35); p=0.002; Sugary beverages excluding juice: 0.70 (0.07, 1.33); p=0.03; Sugary beverages excluding juice and dairy: 0.69 (0.06, 1.32); p=0.03 | Model Adjustments:; - TEI: yes; - Key confounders: age, race and/or ethnicity, anthropometry at baseline, human milk feeding; - Other: Maternal height; soluble fiber; Limitations:; - Did not account for key confounders: socioeconomic position, physical activity, diet quality, smoking, parity; - Start of follow-up and exposure do not coincide; High missing data; No preregistered data analysis plan; Funding:; NIDDK; Gerber Foundation; National Institute of Environmental Health Sciences
Cahill, 2012^184^; PCS, U.S.; Analytic N=58; Participant Characteristics at Baseline:; Postpartum, low-income women with overweight/obesity, with infants 0-4mo; - Age: Mean (SD)=28.0 (0.7)y; - Female: 100%; - Race/ethnicity: White 35%; African American 12%; Hispanic 53%; - SEP: ≥College graduate 26%, Partial college 43%, ≤High school 14%, ; Living with spouse/partner 83%; - Anthropometry: Mean (SD): Weight, 84.8 (2.4) kg; Body fat %, 41.3 (0.8); Waist circumference, 99.7 (2.0) cm; BMI, 32.0 (0.8) kg/m2; - Physical activity: Aerobic exercise, Mean (SEM)=1.1 (0.4) hr/wk; - Smoking: NR; - Diet quality: NR; - Parity: All with parity ≤3 (inclusion criteria); - TEI: ~3100 kcal/d (? Units not given in text or table); Excluded from Study or Analysis: BMI <25 kg/m2; <18 or >40y; infant age >4 mo; annual household income >185% of poverty line; ethnicity other than Hispanic, African American, or white; inability to read, speak, and write English; Parity >3; participation in previous weight-loss studies; pregnancy; diabetes; missing data; energy intake below cutoff values (not indicated) | Exposure: Fruit juice intake (not clear if 100% fruit juice); Comparator: Fruit juice intake (continuous; svg/d); Exposure Assessment Methods and Timing:; Validated FFQ; represents usual intake Baseline, 10wk; - [underlined: Study beverage intake at baseline]: Fruit juice intake, mean: ~0.8 svg/d; Outcome Assessment Methods and Timing:; - Weight measured to nearest 0.1 kg via electronic scale on one occasion without shoes in light clothing; Height measured to nearest 0.1 cm using wall-mounted stadiometer; Body fat percentage measured via electronic scale on one occasion without shoes in light clothing; - Baseline, 10wk | [underlined: Postpartum Weight Change over 10wk], kg, Linear regression; Change per svg/d increase:; β: −0.247, P=NS | Model Adjustments:; - TEI: no; - Key confounders: anthropometry at baseline; - Other: gestational weight gain; Limitations:; - Did not account for key confounders: age, race and/or ethnicity, SEP, physical activity, diet quality, smoking, parity, human milk feeding; - Exposure not clearly defined, No preregistered data analysis plan; Funding:; Texas Department of Health Minority Education Grant, TX Coordination Board
Davis, 2017^185^; PCS, Study of Women, Infant Feeding and Type 2 Diabetes After GDM Pregnancy (SWIFT), U.S.; Analytic N=888; Participant Characteristics at Baseline:; Postpartum women with history of gestational diabetes mellitus; - Age: Mean (SD), 32.6 (4.8)y; - Female: 100%; - Race/ethnicity: Non-Hispanic White: 24.1%; Non-Hispanic Black: 7.7%; Asian: 37.1%; Other: 1.9%; Hispanic: 29.3%; - SEP: Education: High school or less: 23.3%, Some college: 27.6%, ≥4y of college: 49.1%; - Anthropometry: Pre-pregnancy BMI: Mean (SD), 29.4 (7.1) kg/m2; - Physical activity: Total physical activity (PA), mean (SD): 46.1 (21.1) met hr/wk Moderate to vigorous PA, mean (SD): 24.7 (15.4) met hr/wk; - Smoking: NR; - Diet quality: egg consumption: ≥5 svg/wk: 20.1%; 2-4 svg/wk: 40%; 1 svg/wk: 22.1%; None: 17.6%; Processed meats: ≥5 svg/wk: 5.3%; 2-4 svg/wk: 27.9%; 1 svg/wk: 27.7%; None: 38.9%; Fried foods (fried chicken, fish, seafood, french fries, onion rings): ≥5 svg/wk: 3.6%; 2-4 svg/wk: 23.4%; 1 svg/wk: 39.8%; None: 33.2%; - Parity: NR; - TEI: Mean (SD), 834.2 (340.9) kcal/d; Excluded from Study or Analysis: no GDM in pregnancy; not singleton birth; gestation <35wk; <20 or >45y; history of diabetes; not a northern CA resident; elevated fasting glucose ≥126 mg/dL, 2hr glucose ≥200 mg/dL at 6-9wk postpartum diagnostic of diabetes, missing data on exposure or outcome; missing glucose tolerance status at 1yr follow-up. | Exposure: Regular soda (with and without caffeine); Comparator: categorical intake (none, <1 svg/wk, ≥2 svg/wk); Exposure Assessment Methods and Timing:; 13-item Caffeine Questionnaire; medium serving size = 12-oz can; participants reported usual serving size as small, medium, or large 6-9wk postpartum; - [underlined: Study beverage intake at baseline:] Cola soda at baseline (svg/wk):; ≥2 (n = 93): 13.5%; ≤1 (n = 189): 27.4%; None (n = 408): 59.1%; Outcome Assessment Methods and Timing:; - Pre-pregnancy weight was self-reported and validated with measurements within 1yr prior to pregnancy. Weight measured (to nearest 0.1 lb) at 6-9wk gestation and 1yr postpartum using a calibrated digital scale. Height measured (to nearest cm) using a stadiometer. Gestational weight gain categories for pre-pregnancy BMI determined by IOM. Postpartum weight retention calculated by subtracting pre-pregnancy weight from weight at 1yr postpartum. Substantial postpartum weight retention (SPWR) defined as ≥5kg weight retention at 1yr postpartum; - Baseline (pre-pregnancy), 6-9wk postpartum, and 1y postpartum | [underlined: Postpartum weight retention ≥5kg over 1y], OR (95% CI), multivariable logistic regression; None: REF; <1 svg/wk: 1.00 (0.66, 1.53); ≥2 svg/wk: 1.61 (0.98, 2.66), P=0.06; P-trend=0.136 | Model Adjustments:; - TEI: no; - Key confounders: SEP (education); anthropometry at baseline; diet quality (fried foods, eggs, processed meats); human milk feeding; - Other: Gestational weight gain; birth weight; glucose tolerance at baseline, transition of glucose tolerance categories from baseline to 1y postpartum; Limitations:; - Did not account for key confounders: age, race and/or ethnicity, physical activity, smoking, parity; - Exposure data only measured at baseline; No information on noncompleters; Funding:; NICHD; NCRR
Mahabamunuge, 2021^186^; PCS, Rise and Sleep Health in Infancy and Early Childhood (SHINE) cohort, U.S.; Analytic N=348; Participant Characteristics at Baseline:; Postpartum women; - Age: 32.7 (5.0)y; - Female: 100%; - Race/ethnicity: White: 47%; Black: 7%; Asian: 14%; Other: 0.6%; Hispanic: 32%; - SEP: Education: 72.1% college graduate; Household income: <$70k: 33.3%, ≥$70k: 64.4%; Marital status: 88.8% married or cohabitating; 10.1% not married or cohabitating; - Anthropometry: Mean (SD) Pre-pregnancy weight: 66.5 (14.8) kg; Pre-pregnancy BMI: 25.2 (5.7) kg/m2; GWG: 13.7 (5.4) kg; - Physical activity: NR; - Smoking: NR; - Diet quality: NR; - Parity: NR; - TEI: NR; Excluded from Study or Analysis: <18y; unable to speak English or Spanish; not a singleton birth; <37wk gestation; diagnosis of psychosocial/mental health condition, sleep disorder or substance use problem, other children enrolled in study; no completion of 1-mo postpartum visit, missing exposure and/or outcome data | Exposure: SSB (100% pure fruit juices, punch, sweetened fruit drinks, sports drinks, Kool-Aid, Tampico, lemonade, Hi-C, cranberry drink, Goya or Vitamin Water, regular sodas or soft drinks, energy drinks); Comparator: Continuous intake (times/d); Exposure Assessment Methods and Timing:; Validated dietary survey, measured as (and reported as): never (reported as 0/d), <1/wk (0/d), 1/wk (1/7 per d), 2–4/wk (3/7 per day), nearly daily or daily (1/d), 2–4/d (3/d), ≥5/d (5/d), refused/do not know (missing); 1mo postpartum (considered “1mo” if between 2-wk and 4-mo postpartum); - [underlined: Study beverage intake at baseline:] 1mo postpartum SSB intake, Mean (SD): 0.7 (1.0) times/d; Outcome Assessment Methods and Timing:; - Clinically measured weight in the electronic health record (pregravid) and research-measured weight. PPWR calulated as difference between pregravid and 6mo postpartum weight. Substantial PPWR (SPPWR) defined as increase of ≥5kg at 6mo postpartum from pre-pregnancy weight; - At prepregnancy (pregravid) and 6mo (±8wk) | [underlined: Postpartum weight retention], kg, Linear regression, β (95% CI); SSB intake/d at 1mo postpartum: 0.52 (0.03, 1.00); [underlined: Substantial PPWR], Logistic regression, OR (95% CI); SSB intake/d at 1mo postpartum: 1.17 (0.92, 1.52) | Model Adjustments:; - TEI: no; - Key confounders: age, race and/or ethnicity, socioeconomic position (household income), anthropometry at baseline (pre-pregnancy BMI); - Other: GWG; Limitations:; - Did not account for key confounders: physical activity, smoking, parity, diet quality, human milk feeding status; - Start of follow-up and exposure do not coincide; High attrition/missing data; No preregistered data analysis plan; Timing of pregravid weight NR; Measured intake categorically but analyzed ordinally; Funding:; NIDDK

a Abbreviations: BMI: body mass index; CI: confidence interval; d: day(s); EMR: electronic medical record; FFQ: food frequency questionnaire; g: gram(s); GWG: gestational weight gain; kcal: kilocalorie(s); kg: kilogram(s); IOM: Institute of Medicine; LNCSB: low- and no-calorie sweetened beverage(s); m: meter(s); mg: milligram(s); min: minute(s); mL: milliliter(s); N/A: not applicable; NIDDK: National Institute of Diabetes and Digestive and Kidney Diseases; NCRR: National Center for Research Resources; NIH: National Institutes of Health; NR: not reported; NS: not significant; OR: odds ratio; PCS: prospective cohort study; PPWR: postpartum weight retention; REF: reference group; RCT: Randomized controlled trial; SD: standard deviation; SE: standard error; SEP: Socioeconomic position; SSB: sugar-sweetened beverage(s); svg: serving(s); TEI: total energy intake; wk: week(s); y: year(s)

Table 20 Risk of bias for observational studies examining SSB consumption in individuals during pregnancy and gestational weight gain^a^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Figueroa, 2020 ^176^ | HIGH | HIGH | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Guilloty, 2015 ^177^ | HIGH | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | HIGH
Lai, 2019 ^178^ | HIGH | LOW | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | HIGH
Olaffsdottir, 2006 ^179^ | HIGH | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Renault, 2015 ^180^ | HIGH | SOME CONCERNS | LOW | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | HIGH
Samano, 2022 ^181^ | HIGH | HIGH | HIGH | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | HIGH
Stuebe, 2009 ^182^ | HIGH | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | HIGH

a Possible ratings of low, some concerns, high, very high, no information, or not applicable were determined using the “Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)” tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602. )

Table 21 Risk of bias for observational studies examining SSB consumption in individuals during postpartum and postpartum weight change^b^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Alderete, 2020 ^183^ | HIGH | SOME CONCERNS | SOME CONCERNS | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Cahill, 2012 ^184^ | HIGH | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Davis, 2017 ^185^ | HIGH | LOW | LOW | LOW | HIGH | LOW | LOW | HIGH
Mahabamunuge, 2021 ^186^ | HIGH | LOW | LOW | LOW | SOME CONCERNS | LOW | LOW | HIGH

b Possible ratings of low, some concerns, high, very high, no information, or not applicable were determined using the “Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)” tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602. )