# Results

## Literature search and screening results

Articles included in this systematic review were identified from literature searches conducted to identify all potentially relevant articles for 5 systematic reviews assessing the relationship between beverage consumption (SSB, dairy milk and milk alternatives^†^; beverage patterns^‡^; low- and no-calorie sweetened beverages^§^; and 100% juice^**^) and growth, body composition, and risk of obesity. The literature search (Appendix 4) yielded 36,223 search results after the removal of duplicates (Figure 2). Dual-screening resulted in the exclusion of 33,121 titles, 2,552 abstracts, and 463 full-text articles. Reasons for full-text exclusion are in Appendix 5. Six additional articles with data on SSB and relevant outcomes were identified from the manual search, and 4 articles were identified as part of the complementary feeding and growth, body composition, and risk of obesity systematic review. In total, the body of evidence examining SSB included 186 articles, some of which examined multiple populations:

- Infants, children, and adolescents: 111 articles^1–111^
- Adults and older adults: 66 articles^29,50,112–175^
- Individuals during pregnancy and postpartum: 11 articles^176–186^

† Raynor HA, Deierlein AL, Gardner CD, . Dairy Milk and Milk Alternatives and Growth, Body Composition, and Risk of Obesity: A Systematic Review. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review; 2025. 10.52570/NESR.DGAC2025.SR03

‡ Raynor HA, Deierlein AL, Gardner CD, . Beverage Patterns and Growth, Body Composition, and Risk of Obesity: A Systematic Review. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review; 2025. 10.52570/NESR.DGAC2025.SR02

§ Raynor HA, Deierlein AL, Gardner CD, . Low- and No-Calorie Sweetened Beverages and Growth, Body Composition, and Risk of Obesity: A Systematic Review. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review; 2025. 10.52570/NESR.DGAC2025.SR04

** Deierlein AL, Raynor HA, Andres A, . 100% Juice and Growth, Body Composition, and Risk of Obesity: A Systematic Review with Meta-Analysis. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review; 2025. 10.52570/NESR.DGAC2025.SR05

Figure 2 Literature search and screen flowchart

The literature searches in PubMed, Embase, Cochrane, and CINAHL, retrieved 36,223 records after removing duplicates. 167 were included from existing reviews. 38 were found with manual search methods. 33,121 titles, 2,552 abstracts, and 463 full-texts were excluded. 292 articles were included across the five systematic reviews examining beverage consumption and growth, body composition, and risk of obesity.

## Infants, children, and adolescents

### Description of the evidence

The body of evidence examining the relationship between SSB consumption and growth, body composition, and risk of obesity in infants and young children (up to age 24 months), children, and adolescents included 111 articles, which are summarized in Table 12. Risk of bias assessments for each article are summarized in Table 13 (RCT) and Table 14 (observational).

#### Population

Of the 111 articles in infants, children, and adolescents, 5 articles from randomized controlled trials (RCT) came from 4 separate trials (3 parallel design and 1 cluster RCT). One hundred seven articles from cohort studies (106 from prospective cohort studies (PCS) and 1 from a retrospective cohort study (RCS)) came from 89 independent cohorts. Wang et al included both trial and cohort data.^95^ Twenty-three countries were represented in the included articles, with 44 articles coming from the U.S., 16 articles from Australia, 8 articles from the Netherlands, 6 articles from the U.K., 6 articles from Denmark, and the remainder from Germany, South Korea, Canada, China, Belgium, Brazil, Chile, Colombia, Finland, Iran, Mexico, New Zealand, Peru, Portugal, Scotland, Singapore, Spain, and Uruguay. One RCT^22^ and 6 articles from observational studies^7,28,35,77,85,90^ reported receiving industry funding; funding sources for all articles are reported in Table 12.

##### Randomized controlled trials

Among the 5 articles describing 4 RCT, mean baseline age ranged from 8 to 16 years. Relatively even numbers of male and female participants were studied – the percent of female participants ranged from 45% to 54% - and analytic sample sizes ranged from N=103 to N=1633. All but one article, conducted in China,^95^ provided some information on race and/or ethnicity. In de Ruyter et al^15^ and Katan et al,^46^ both of which reported results from the Double-blind Randomized INtervention study in Kids (DRINK) trial in the Netherlands, 78% of participants were of Dutch ancestry and the remainder were of “non-Western” ancestry. In Ebbeling et al (2012),^22^ 50% of participants were White, 21% Black, 4% Asian, and 16% multiple or other; 19% of participants reported Hispanic ethnicity. Ebbeling et al (2006)^23^ reported that 64% of participants were non-White.

All 4 trials reported information on socioeconomic position (SEP); 2 of the 4 independent trials included >50% of participants with parents having at least some college or vocational school,^15,22,46^ and the cluster RCT included 67% of participants with parental education >9 years.^95^ Of the trials that reported information on household income,^22,23^ all income levels were relatively evenly represented. Two trials had inclusion criteria for weight status: Ebbeling et al (2012)^22^ required that participants have baseline BMI ≥85^th^ percentile and Ebbeling et al (2006)^23^ only included participants with baseline BMI >25^th^ percentile. All trials required that participants be habitual SSB consumers.

##### Observational studies

The 107 articles from observational studies were from 89 independent cohorts; 14 articles reported secondary analyses of data from RCTs. Sample sizes ranged from N=21 to N=142,668 participants, with 52 articles involving over 1000 participants each. Lengths of follow-up ranged from 16 weeks to 30 years. Seventeen articles studied infants and young children up to 24 months, of which 3^41,56,78^ also reported outcomes for older children. Twenty-four articles included children with a mean baseline age of 2-4 years and 51 articles included participants with a mean age between 5 and 13 years at baseline. Fourteen articles included study populations with a mean baseline age older than 13 years. Five articles included 100% female participants; the remainder included relatively even numbers of male and female participants.

Sixty-seven of the 107 articles from cohort studies reported race and/or ethnicity data. Of these, 36 articles were from studies in predominantly White populations, and 14 articles reported that >50% of participants were from racial and/or ethnic minority groups. Seven articles were in 100% non-White populations (e.g., 100% Asian, Hispanic, Black, or Aboriginal/Torres Strait Islander); 6 articles reported only information on immigrant status and 4 articles from Australia reported country of origin data. Seventy-four articles reported information on SEP, representing a broad spectrum of education, income, and other measures of SEP.

#### Intervention/exposure and comparator

The intervention or exposure of interest for this systematic review question was SSB. Eligible comparators were consumption of different amounts of SSB (including no consumption and versions diluted with water), water, or LNCSB.

##### Randomized controlled trials

Two articles from 1 RCT directly compared SSB with LNCSB.^15,46^ In the other 3 trials,^22,23,95^ participants were encouraged to reduce consumption of SSBs, usually by replacing with water and/or LNCSB. Trial duration ranged from 25 weeks to 18 months, and all collected information on compliance to the assigned intervention or control group.

##### Observational studies

All articles from cohort studies examined varying levels of SSB intake as their exposure and comparator of interest. Thirty-nine articles collected exposure data via parent/caregiver survey or interview (most commonly completed by mothers), 36 articles used food frequency questionnaires to measure SSB intake, 27 articles assessed SSB intake through dietary recalls and 5 articles used weighed food and beverage records. Fifty-four articles compared SSB intake continuously and 45 articles compared different intake levels of SSB (e.g., tertiles of SSB servings per week); 8 articles employed both continuous and categorical comparators. The units used to measure SSB intake varied across articles (e.g., servings, ounces, grams, cups, kilocalories), as did the time scale for consumption (e.g., intake per day or week). Thirty-six articles assessed exposure at baseline only, while 71 measured SSB intake at more than one time point.

#### Outcomes

##### Randomized controlled trials

Outcomes examined by the RCTs included BMI,^22,23,95^ BMI z-score,^15,46,95^ weight,^15,22,46,95^ height,^15,22,46,95^ height-for-age z-score,^15^ waist-to-height ratio,^15^ body fat percentage,^15,22,46^ fat mass,^15,46^ waist circumference,^15,46^ and sum of skinfolds.^15,46^ All outcomes in the RCTs were measured by study personnel.

##### Observational studies

Of the 107 articles from cohort studies, 50 articles reported growth outcomes (e.g., BMI z-score, height, weight), 39 articles reported body composition outcomes (e.g., percent body fat, waist circumference), and 60 articles included risk of obesity outcomes (e.g., BMI, risk of overweight). Eleven articles included outcomes based on self- or parent-reported height and/or weight, which were used to calculate BMI.^7,27,36,50,57,60,75,79,92,93,111^ All other articles reported outcomes measured by study personnel.

#### Studies included in meta-analyses

Five articles from 4 RCTs^15,22,23,46,95^ and 70 of 107 articles from 63 PCS^2,4,7,10,11,13,14,19,24–28,32,34–36,38,40,42–44,48–54,56,58–63,66–68,70,72,73,75–80,82–86,88–92,94–96,101,102,104–110^ were included in the meta-analyses. Articles were excluded from meta-analysis because NESR analysts were unable to estimate an effect size^8,16–18,21,29,39,47,98^ or too few studies reported the particular exposure or outcome.^1,3,5,6,12,30,31,33,37,41,45,55^ ^,57,65,69,71,74,87,97,111^

##### Randomized controlled trials

All RCTs were included in the meta-analysis, so the study and participant characteristics were the same as for the full body of evidence. The only outcome with sufficient data to permit meta-analysis was change in BMI over time.

##### Observational studies

Of the studies included in the meta-analysis, the majority (29 articles) were conducted in the United States.^7,11,13,26–28,35,36,48,50–53,56,59–61,66,72,75,77,79,80,84,86,91,92,96,101^ Eleven articles came from studies in Australia^4,34,42,44,49,67,88,105–107,110^; 4 each from Denmark^43,90,108,109^ and the Netherlands^54,85,94,102^; 3 each in China^38,95,104^ and Germany^58,70,89^; 2 each in Brazil,^24,83^ Mexico,^10,25^ and the United Kingdom^32,63^; and 1 each in Belgium,^14^ Canada,^19^ Colombia,^82^ Finland,^73^ Iran,^68^ Peru,^2^ Scotland,^62^ Singapore,^78^ South Korea,^40^ and Uruguay.^76^ Analytic sample size and distributions of race and/or ethnicity and measures of socioeconomic position were similar to the full body of evidence. Eight articles included infants and young children age birth up to 24 months^54,56,63,75,78,84,91,101^ and 62 included children and adolescents age 2 up to 19 years.^2,4,7,10,11,13,14,19,24–28,32,34–36,38,40,42–44,48–53,58–62,66–68,70,72,73,76,77,79,80,82,83,85,86,88–90,92,94–96,102,104–110^

Twenty-seven articles compared SSB intake continuously^11,26–28,36,40,42,43,50,52,58–61,66,72,73,78,79,83,85,86,102,105–108^ and 31 articles compared different categories of SSB intake^2,10,14,19,28,32,34,35,54,56,62,63,68,75–78,82,84,88–92,94,96,101,104,109^ 2019^,110^; change in SSB intake was also analyzed continuously (15 articles)^7,13,24,27,43,44,48,51–53,60,61,67,70,102^ and categorically (6 articles).^4,25,42,59,95,109^ Insufficient data were identified for meta-analyses of the following outcomes: change in BMI or BMI z-score (37 articles),^2,4,7,13,24–27,34,42–44,48,51–53,56,59–61,67,70,72,76,82,83,88,90,92,94,95,102,105–109^ risk of overweight or obesity later in childhood (19 articles),^10,14,19,28,38,49,54,59,61,62,68,75,80,89,91,94,96,104,110^ risk of overweight or obesity in adulthood (5 articles),^36,50,73,79,107^ BMI z-score at follow-up (17 articles),^11,32,35,40,54,58,63,66,73,77,78,84,86,88,101,102,104^ and percent body fat (6 articles).^11,28,40,58,85,108^

### Synthesis of the evidence

Articles in infants, children, and adolescent populations were synthesized together. Since energy intake is an important covariate when interpreting studies on the relationship between SSB consumption and growth, body composition, and risk of obesity, whether or not articles adjusted for TEI was considered within the evidence synthesis.

Most articles (65 of 111, 59%) reported at least one effect or association where SSB predicted unfavorable growth and body composition outcomes, such as increases in or greater weight-for-age, BMI-for-age, fat mass, or waist circumference. No articles reported an effect or association where SSB were beneficial. In several articles, findings were not consistent when stratified by sex, racial and/or ethnic group, or baseline weight status; these inconsistencies are described in greater detail in the sections below.

#### Growth outcomes

##### Randomized controlled trials

Four of the 5 articles from RCTs assessed growth outcomes, including BMI z-score, weight, height, and height-for-age z-score. Among the 3 articles that measured BMI z-scores, all reported a statistically significant difference between treatment and control groups, in which those either randomized to receive SSB^15,46^ or who did not receive a SSB reduction intervention^95^ had higher BMI z-scores at the end of the intervention. Katan et al^46^ found that participants with a higher baseline BMI experienced a higher effect of treatment (i.e., among those randomized to LNCSB intervention, participants with a higher baseline BMI had a lower BMI z-score at the end of intervention than those with lower baseline BMI). However, in children who received SSB, initial BMI had little impact on the course of BMI z-scores.^46^

##### Observational studies

Fifty articles from observational studies assessed growth outcomes, including BMI z-score or standard deviation score (SDS) (42 articles), weight (4 articles),^2,72,89,106^ adiposity rebound (2 articles),^33,41^ BMI or BMI SDS trajectory (3 articles),^31,35,55^ weight-for-age z-score (2 articles),^12,57^ weight-for-height z-score, (1 article),^12^ weight-for-length z-score (1 article),^3^ weight SDS (1 article),^55^ height SDS (1 article),^55^ and height (1 article).^65^

Among the articles that measured BMI z-scores or SDS, 23 reported null associations with SSB intake,^9,11,12,21,28,29,40,42,47,48,53,56,58,59,63,74,76,89,90,97,100,103,104^ 14 reported that SSB was related to increases in these outcomes,^8,13,20,24,26,44,66,67,77,93–95,98,105^ and 5 included mixed findings (i.e., both null and unfavorable findings across subgroups by age, gender, or analytic model).^16,55,78,84,106^ Broadly, articles in children and adolescents included more associations between SSB intake and higher BMI z-scores or SDS compared with articles assessing the relationship in infants and young children.

Articles assessing weight as an outcome included a mix of null and unfavorable associations. Newby et al^72^ and Traub et al^89^ both found no association between SSB intake and weight change over 6-12 months and 1 year, respectively. In contrast, in a sample of 1,813 Peruvian children with high risk of overweight, daily SSB consumption was associated with greater weight gain after 4 years compared with never-consumption.^2^ Zheng et al^106^ used two different models to examine the relationship between SSB intake and weight, both of which were just outside the range of statistical significance but showed trends toward a greater increase in weight with each 100 g/d increase in SSB consumption.

In a cohort of young children in the Netherlands, Leermakers et al^54^ found a direct association between SSB intake and higher BMI SDS in girls, but not in boys. A similar gender pattern was seen in this relationship when measuring weight SDS, though findings for girls were just outside the range of statistical significance.^55^ Two articles assessing BMI or BMI SDS trajectory as an outcome reported null associations overall,^31,55^ while 1 article found an unfavorable association between soda intake and BMI trajectory.^35^ Higher SSB intake was associated with earlier adiposity rebound in both articles assessing this outcome in infants and young children,^33,41^ but the association was null in children older than 24 months.^41^ In a sample of young Latino children ages 12-24 months at baseline, Chaidez et al^12^ found an association between SSB intake and greater change in weight-for-height z-score, but not weight-for-age z-score, at a mean age of 27.7 months. In this same article, change in BMI z-score trended toward a direct association with SSB intake.^12^ An article using data from the Infant Feeding Practices Study II cohort also found no association with weight-for-age z-score.^57^ In articles assessing height outcomes, one found no association^65^ and another found a relationship between SSB intake and increased height SDS in high versus low intake in boys, but not in girls.^55^

#### Body composition outcomes

##### Randomized controlled trials

Three articles reported body composition outcomes.^15,22,46^ In the DRINK trial,^15^ participants randomized to LNCSB had a smaller mean increase in waist circumference after 18 months compared to those randomized to SSB; this effect was enunciated in those with higher baseline BMI randomized to LNCSB.^46^ De Ruyter et al^15^ also found an unfavorable effect of SSB on fat mass and sum of skinfolds compared with LNCSB; baseline BMI did not relate to the effect for either outcome.^46^ One article from the U.S. found no difference in change in body fat percentage after 1 year between adolescents randomized to a noncaloric beverage intervention compared to another group who maintained usual beverage intake.^22^ However, this was the only RCT article that adjusted for TEI. De Ruyter et al^15^ found a lower increase in the sum of skinfolds after 18 months in those randomized to LNCSB compared with those randomized to SSB.

##### Observational studies

Thirty-nine articles from observational studies reported body composition outcomes, including body fat mass or percentage (22 articles), waist circumference (20 articles), sum of skinfolds (7 articles),^37,43,78,82,102,108,109^ waist-to-height ratio (2 articles),^32,89^ waist-to-hip ratio (1 article),^104^ and lean mass (1 article).^6^ The articles with body fat mass or percentage outcomes included 7 that demonstrated unfavorable associations with SSB intake,^8,11,25,28,77,101,105^ ^12^ articles reporting only null associations,^1,5,6,37,40,45,54,55,58,71,103,104^ and 3 articles reporting mixed findings based on differences in sex-stratified results.^34,51,85^ Gopinath et al^34^ found an association with higher frequency of SSB intake and higher change in body fat percentage over 5 years in girls, but not in boys, while 2 articles found associations with SSB intake in adolescent boys and higher percent body fat at follow up, either after 2 years^51^ or 25-30 years later.^85^ In these studies, no association was seen between SSB intake in adolescent girls and percent body fat at follow-up. The single article examining lean body mass as an outcome did not find a relationship between SSB intake in adolescents and lean mass at 20 years old, neither for the total sample nor when stratified by sex.^6^

Nine of the 20 articles examining SSB intake and waist circumference did not find an association,^2,30,40,74,^102104^,108,109^ while 8 articles found unfavorable associations^8,10,25,28,47,53,68,107^ and 3 articles found mixed results when stratified by sex^4,34^ or type of SSB.^37^ Hasnain et al^37^ found a relationship between fruit/vegetable juice intake in childhood (not confirmed to be 100% juice) and higher waist circumference in adolescence; this relationship was not significant for SSB intake and waist circumference. Gopinath et al^34^ found a relationship between SSB intake in girls (but not in boys) and waist circumference 5 years later, while Ambrosini et al^4^ found a higher percent change in WC in adolescent boys in higher tertiles of SSB consumption after 3 years of follow-up; this relationship in girls was in the same direction, though just outside the range of statistical significance. Articles assessing the relationship between SSB intake and waist-to-height ratio^89^ or waist-to-hip ratio^104^ did not find an association with either outcome.

Of the articles with skinfold thickness outcomes, 4 articles reported null associations,^43,82,102,109^ 1 article found an unfavorable association with SSB intake,^108^ and 2 articles reported mixed findings.^37,78^ One article using data from the GUSTO cohort in Singapore assessed the relationship between SSB intake measured at 18 months and at 5 years and the sum of skinfold thickness measured at 6 years. No association was found for SSB intake at 18 months and sum of skinfolds at 6 years; however, when using exposure data measured at 5 years, an increase of 0.87 centimeters was seen 1 year later for every 100 milliliters of SSB consumed daily.^78^ Similar to the mixed findings for waist circumference, Hasnain et al^37^ found a relationship between fruit/vegetable juice intake in childhood (not confirmed to be 100% juice) and higher sum of skinfolds in adolescence; this relationship was not significant for SSB intake and sum of skinfolds.

#### Risk of obesity outcomes

##### Randomized controlled trials

Three articles assessed change in BMI, including the cluster RCT in children and 2 articles in adolescents.^22,23,95^ In the cluster RCT, children in schools randomized to the intervention aimed at reducing SSB consumption had a lower BMI increase compared to children in schools receiving no intervention.^95^ Ebbeling et al (2006) found no difference in BMI change overall between groups; however, they noted a statistically significant reduction in BMI for those in the upper tertile of baseline BMI randomized to the noncaloric intervention, compared to the usual SSB intake control.^23^ In Ebbeling et al (2012),^22^ which included a 1-year intervention and a follow-up visit 1 year later, participants randomized to a noncaloric beverage intervention had a lower change in BMI at 1 year compared to the control group; this difference was not significant at the 2-year follow-up. Subgroup analyses revealed that any differences in change in BMI were driven by Hispanic participants: no difference between groups was found at either time point for non-Hispanic participants, but in Hispanic participants an unfavorable effect of maintaining usual SSB intake on change in BMI was seen at both time points, compared with the noncaloric beverage intervention group.

##### Observational studies

Sixty articles from observational studies assessed risk of obesity outcomes, including BMI or change in BMI (31 articles), risk of overweight or obesity (30 articles), and weight status (5 articles). Among articles with BMI or BMI change as an outcome, 12 articles found unfavorable associations with SSB intake,^2,8,61,62,70,82,83,86,87,102,107,108^ 14 found no association,^13,25,32,34,37,43,51,52,60,72,81,85,109,111^ and 5 found mixed associations.^4,7,27,73,88^ Among these, 2 articles found unfavorable associations between SSB intake and BMI in adulthood^73^ or percent change in BMI in adolescence^4^ in girls, but not in boys. In contrast, Berkey et al^7^ reported an unfavorable association for boys – but not for girls – before adjusting for TEI; however, there was no association for girls and boys after TEI adjustment. In an article reporting results from the Growing Up Today Study (GUTS) II cohort, Field et al^27^ found unfavorable associations between sports drink consumption and change in BMI; no association was seen for soda consumption. Lastly, Thurber et al^88^ reported an association between SSB intake and BMI intercept at 3-year follow-up, but no associations were noted for annual BMI change, BMI change over 3 years, or BMI change over 3 years by number of occasions of SSB intake on the preceding day.

Of the articles examining SSB intake and risk of overweight or obesity, 11 found a direct, unfavorable association,^2,10,19,39,61,75,78,80,91,94,107^ 11 reported only null associations,^14,28,38,49,54,64,79,89,99,104,110^ and 8 demonstrated mixed findings.^4,36,59,62,70,73,96,102^ In articles with weight status (e.g., weight gain, weight maintenance) as an outcome, 3 articles found null associations with SSB intake and weight status^18,69,98^ and 2 articles reported mixed findings.^17,50^

#### Meta-analysis

##### Change in BMI

A meta-analysis examining the relationship between change in SSB intake, measured continuously, and change in BMI over time included 34,584 children (age approximately 3 to 16 years) and 19 observations (i.e., effect sizes) from 15 articles^7,13,24,27,43,44,48,51–53,60,61,67,70,102^ (Figure 3, Table 5, Figure A 1 through Figure A 5). For each additional 8 oz/d in SSB over time, BMI increased by 0.03 kg/m^2^ (95% CI: 0.02, 0.03) on average. Heterogeneity, as measured by σ^2^, I^2^, and the 95% PI, was low.

Results for change in SSB intake, measured categorically, and change in BMI over time were mixed: decreasing intake versus no change in intake was not significantly associated with a change in BMI, but increasing intake versus no change in intake was associated with an increase of 0.12 kg/m^2^ (95% CI: 0.04, 0.19) on average over time (Table 5, Figure A 7, Figure A 8, Table A 6, Table A 7). The results of the tests of funnel plot asymmetry were mixed (Figure A 6, Figure A 9).

Figure 3 Meta-analysis of change in SSB intake in children (continuous, 8 oz/d), and change in BMI.*

* BMI: body mass index; d: day; ML: multilevel; oz: ounce; SSB: sugar-sweetened beverage; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of change in SSB (measured continuously, per 8 oz/d intake) and change in BMI in children. Overall, there is an increase in BMI in children with each additional increase of 8 oz/d SSB: 0.03 (95% CI: 0.02, 0.03).

Table 5 Summary of meta-analyses in children

Exposure and outcome | Summary statistics for main analyses | Sample size
RCT
SSB intervention and change in BMI | Pooled MD: −0.30 (−0.52, −0.07), p=0.01, I^2^: 95.9%, 95% PI: −0.76, 0.17 | 4 observations from 4 articles, including 2,422 children
PCS
Change in BMI
Change in SSB and change in BMI | Pooled slope: 0.03 (0.02, 0.03), p<0.01, I^2^: 0.0%, 95% PI: 0.02, 0.03 | 19 observations from 15 articles, including 34,584 children
Change in SSB (Decrease versus no change/increase) and change in BMI | Pooled slope: 0.02 (−0.14, 0.18), p=0.82, I^2^: 6.2%, 95% PI: −0.18, 0.21 | 8 observations from 3 articles, including 2,294 children
Change in SSB (Increase versus no change/decrease) and change in BMI | Pooled slope: 0.12 (0.04, 0.19), p<0.01, I^2^: 0.0%, 95% PI: 0.04, 0.19 | 11 observations from 4 articles, including 6,752 children
SSB intake at baseline (per 8 oz/d) and change in BMI | Pooled slope: 0.09 (0.02, 0.16), p=0.01, I^2^: 92.4%, 95% PI: −0.13, 0.31 | 15 observations from 12 articles, including 17,066 children
SSB intake at baseline (Any versus none/rare) and change | Pooled slope: 0.07 (−0.01, 0.14), p=0.07, I^2^: 30.4%, 95% PI: −0.06, 0.19 | 11 observations from 5 articles, including 6,752 children
SSB intake at baseline (Some versus less) and change in BMI | Pooled slope: 0.14 (−0.01, 0.30), p=0.19, I^2^: 68.7%, 95% PI: −0.22, 0.51 | 24 observations from 4 articles, including 17,578 children
Risk of obesity
SSB intake at baseline (per 8 oz/d) and risk of obesity | OR: 1.13 (0.97, 1.31), p=0.13, I^2^: 76.3%, 95% PI: 0.88, 1.45 | 6 observations from 5 articles, including 11,883 children
SSB intake at baseline (Any versus none) and risk of obesity | OR: 1.40 (1.04, 1.89), p=0.03, I^2^: 52.5%, 95% PI: 0.80, 2.45 | 9 observations from 4 articles, including 5,488 children
SSB intake at baseline (More versus less) and risk of obesity at follow up | OR: 1.42 (1.15, 1.75), p<0.01, I^2^: 54.5%, 95% PI: 0.78, 2.57 | 37 observations from 10 articles, including 22,295 children
SSB intake at baseline (per 8 oz/d) and risk of obesity in adulthood | OR: 1.14 (0.97, 1.33), p=0.10, I^2^: 40.1%, 95% PI: 0.88, 1.47 | 9 observations from 5 articles, including 5,305 children
BMI z-score
SSB intake at baseline (per 8 oz/d) and BMI z-score at follow up | Pooled slope: 0.04 (0.00, 0.08), p=0.03, I^2^: 88.4%, 95% PI: −0.04, 0.12 | 9 observations from 9 articles, including 5,760 children
SSB intake at baseline (Any versus none/rare) and BMI z-score at follow up | Pooled slope: 0.09 (0.05, 0.12), p<0.01, I^2^: 0.0%, 95% PI: 0.05, 0.12 | 10 observations from 4 articles, including 17,858 children
SSB intake at baseline (Some versus less) and BMI z-score at follow up | Pooled slope: 0.04 (−0.00, 0.09), p=0.12, I^2^: 15.8%, 95% PI: −0.04, 0.12 | 20 observations from 8 articles, including 8,475 children
Percent body fat
SSB intake at baseline (per 8 oz/d) and percent body fat at follow up | Pooled slope: 1.18 (0.22, 2.14), p=0.02, I^2^: 64.3%, 95% PI: −0.72, 3.08 | 8 observations from 5 articles, including 1,427 children

In a meta-analysis of 4 RCTs ^15,22,23,95^ examining the relationship between SSB interventions and change in BMI, the results showed a statistically significant relationship favoring treatment (Table 5, Figure A 10 through Figure A 14). In other words, when children were randomized to interventions meant to decrease SSB intake, they had a greater decrease in BMI relative to control groups.

For each additional 8 oz/d of SSB at baseline, BMI increases over time by 0.09 (95% CI: 0.02, 0.16) kg/m^2^ on average (Table 5, Figure A 15, Figure A 21). Any intake, versus no or rare SSB intake at baseline was not significantly associated with change in BMI (Table 5, Figure A 23, Figure A 24, Table A 8) and consuming some, versus less, SSBs at baseline was not significantly associated with change in BMI (Figure A 26); however, the pooled estimates trended toward greater increases in BMI with higher SSB intake. The results of the funnel plot asymmetry analyses were mixed and it is unclear whether non-reporting bias is a concern (Table 5, Figure A 22, Figure A 25, Figure A 27, Table A 9).

##### Risk of obesity

Any SSB intake at baseline, versus no intake, was associated with greater odds (OR=1.40; 95% CI: 1.04, 1.89) of overweight and/or obesity at follow-up during childhood (Table 5, Figure A 31, Table A 10). More (versus less) SSB intake at baseline was significantly associated with greater odds (OR=1.42; 95% CI: 1.15, 1.75) of overweight and/or obesity (Table 5, Figure A 32, Figure A 33, Table A 11).

SSB intake at baseline, measured continuously, did not significantly predict risk of overweight and/or obesity at follow-up during childhood (Figure A 28 through Figure A 30). Both TEI adjustment and baseline weight status significantly moderated the association. Likewise, baseline SSB intake was not associated with risk of overweight and/or obesity at follow-up during adulthood (Figure A 34 through Figure A 38). No subgroup analyses revealed statistically significant moderators.

##### BMI z-score

BMI z-score is on average 0.04 SD (95% CI: 0.0, 0.08) higher with each additional 8 oz/d SSB at baseline (Table 5, Figure A 39 through Figure A 46). None of the subgroup analyses showed significant differences. Any intake versus no/rare SSB intake at baseline was also associated with BMI z-score at follow-up (Table 5, Figure A 47, Figure A 48, Table A 12),^35^ showing a statistically significant, detrimental relationship. Consuming some SSB intake versus less SSB intake at baseline was not associated with BMI z-score at follow-up (Table 5, Figure A 49 through Figure A 52, Table A 13).

##### Percent body fat

Eight observations from 5 articles^11,28,40,58,108^ were included in a meta-analysis of 1,427 children. Analysis showed a statistically significant, detrimental association between SSB intake at baseline, measured continuously, and percent body fat at follow-up. Each added 8 oz serving increased body fat by over one percentage point. Both I^2^ and the 95% confidence interval suggested substantial heterogeneity (Table 5, Figure A 53, Figure A 58).

Due to the limited number of results in each exposure-outcome group, dose-response analyses were not conducted. Study-by study influence analyses generally suggested consistent findings; removing individual observations from each model did not substantially change the results.

### Conclusion statement and grade

The 2025 Dietary Guidelines Advisory Committee developed and graded a conclusion statement for the systematic review question: “What is the relationship between sugar-sweetened beverage consumption and growth, body composition, and risk of obesity?” based on review of the totality of evidence in infants, children, and adolescents (see Table 6).

Table 6 Conclusion statement and grade for sugar-sweetened beverage consumption and growth, body composition, and risk of obesity in infants, children, and adolescents

Conclusion Statement | Sugar-sweetened beverage consumption by infants, children, and adolescents is associated with unfavorable growth patterns and body composition, and higher risk of obesity in childhood up to early adulthood. This conclusion statement is based on evidence graded as moderate.
Grade | Moderate
Body of Evidence | 5 RCTs (all in meta-analysis); 107 observational studies (72 in meta-analyses)
Consistency | Consistent directionality of findings across articles; some heterogeneity
Precision | Few concerns with precision
Risk of bias | Some concerns with risk of bias, primarily due to confounding and missing data in observational studies
Directness | Few concerns with directness across studies
Generalizability | Some concerns with generalizability to the US population, particularly in the RCT data, and limited data included in meta-analyses for infants/young children

#### Assessment of the evidence

The body of evidence underlying the conclusion statement above includes 5 articles from 4 RCTs (all included in meta-analysis) and 107 articles from 89 independent observational studies (72 included in meta-analysis). The evidence was graded based on an assessment of 5 grading elements, as described below. In addition, non-reporting bias was also a consideration and was assessed in detail by funnel plot analyses. While funnel plot analyses were not possible for all meta-analyses, those constructed usually showed some asymmetry. From 1 to 5 effect sizes were estimated to be missing from most analyses, which could reflect chance missingness or variation due to systematic differences but could also be due to non-reporting bias (potentially including publication bias).

##### Consistency

In general, articles showed a consistent directionality of effect across GBCO outcomes. All articles from RCTs reported at least one direct effect of SSB consumption on outcomes versus the comparator. Over half of the articles from observational studies also found at least one direct association between SSB and GBCO. Often a mixture of significant and non-significant findings occurred within articles (e.g., when more than one outcome was reported or with subgroup analyses), but all findings represented either a direct effect/association or no effect/association. No articles reported a favorable effect or association. Meta-analysis results showed similar consistency in the direction and magnitude of findings across analyses, with mostly low heterogeneity. No articles reported an indirect effect or association (i.e., SSBs did not show a favorable relationship with any outcome).

##### Precision

There were no concerns with power of the RCTs, and nearly half of all observational studies had sample sizes >1000. For meta-analysis, the number of unique samples was small to moderate, but all analyses had a sizeable pooled sample size (from approximately n=1500 to n=17,000).

##### Risk of bias

Most cohort studies had a high risk of bias due to confounding and missing data. For the meta-analyses, some asymmetry was noted in several funnel plots, suggesting that 1-5 effect sizes may be missing from most analyses, likely due to non-reporting bias.

##### Directness

The articles consistently measured the relationship of interest.

##### Generalizability

This body of evidence had greater representation of different racial and/or ethnic groups and more range in SEP markers than other reviews of beverage types; this was especially apparent in the observational studies. Concerns with generalizability included a lack of trial data for children younger than 8 years old, and the smaller number and proportion of articles eligible for meta-analysis from the infants and young children life stage, compared with children and adolescents.

## Adults and older adults

### Description of the evidence

The body of evidence examining the relationship between SSB consumption and body composition and risk of obesity in adults and older adults included 66 articles, which are summarized in Table 15. Risk of bias assessments for each article are summarized in Table 16 (RCT) and Table 17 (observational).

The 66 included articles consisted of 8 RCTs, all of which were from independent trials, and 58 PCS from 42 independent cohorts. Three of the 8 RCTs were conducted in the United States^131,143,170^; 2 in Mexico^142,173^; and one each in Australia,^149^ Denmark,^154^ and Switzerland.^122^ Twenty-five PCS were conducted in the U.S.^29,50,112–115,118–120,125,126,128,130,133,134,138,153,156,161,163,166,168,172,174,175^; 6 in Australia^123,127,137,155,162,171^; 5 in Spain^116,117,132,135,150^; 3 in Denmark^140,141,160^; 2 in Finland^146,148^; 2 in Mexico^139,169^; 2 in Singapore^152,159^; 2 in the Netherlands^121,158^; 1 each in Belgium,^157^ Brazil,^167^ Canada,^129^ Germany,^165^ Iran,^144^ Italy,^124^ Japan,^145^ Korea,^147^ Norway,^151^ Russia,^136^ and Switzerland^164^; and 1 examining data from the European Prospective Investigation into Cancer and Nutrition (EPIC) study and the DiOGenes (Diet, Obesity, and Genes) project with cohorts from Italy, the UK, The Netherlands, Germany, Denmark.^164^

Multiple cohorts were represented by more than one article in this body of evidence: the Nurses’ Health Study (NHS) was examined in 4 articles,^156,163,168,175^ the Nurses’ Health Study II (NHS II) in 6,^118,156,163,166,168,175^ the Health Professionals Follow-up Study (HPFS) in 4,^156,163,168,175^ the Coronary Artery Risk Development in Young Adults (CARDIA) Study in 2,^130,174^ the PREvención con DIeta MEDiterránea (PREDIMED) in 2,^132,150^ and secondary analyses of data from the PREMIER trial in 2.^125,126^

#### Population

Only 1 study exclusively enrolled an older adult population.^133^ Therefore, no synthesis could be conducted or conclusion drawn about that population specifically, and the synthesis and resulting conclusion statements and grades apply to the broader adult population, including older adults.

##### Randomized controlled trials

Sample sizes for the 8 RCTs ranged from N=27^122^ to N=272^170^ and consisted of predominantly younger adults, with the mean age ranging from 22^173^ to 42 years.^170^ One study exclusively enrolled female participants,^142^ and an additional 3 studies enrolled >70% female participants.^131,170,173^ Three of the 8 studies reported data on race and/or ethnicity, with one reporting 51% White, 20% Black, and 13% Asian participants,^131^ while a second had 54% Black and 40% White participants,^170^ and a third exclusively enrolled 100% Hispanic participants.^142^ SEP data were given in only 2 articles. One reported on education and household income, noting that a majority of participants had an Associate’s/Bachelor’s degree or higher and income >$30,000^131^, and the other reported on education only, noting that 55% of participants had a college degree or higher.^170^

Five of the 8 RCTs exclusively enrolled participants with either overweight or obesity, determined by baseline BMI,^122,142,143,154,170^ while the remaining 3 trials included participants across a broader BMI range.^131,149,173^ Six trials enrolled participants with high habitual SSB consumption at baseline, though the definition of “high intake” varied across studies.^122,131,142,149,170,173^

##### Observational studies

Analytic sample sizes ranged from N=85^120^ to N=117,992^168^ with 40 of the 58 articles analyzing >1,000 participants. Ten studies examined only female participants,^113–115,118,119,161,166,169,171,172^ while an additional 5 considered >70% female participants,^112,138,139,145,163^ and 1 examined only male participants.^158^ The age distribution was broader in the cohort studies than the trials, with average participant age ranging from 25^130,174^ to 67 years,^132^ and possible age ranges spanning young to older adults in the majority of articles.

Of the 30 articles that reported data on race and/or ethnicity, 17 reported predominantly White participants^29,50,112,114,115,125,126,128,138,150,153,156,162,163,168,172,175^; 8 reported predominantly Asian,^147,152,159^ Black,^119,161^ non-White Hispanic,^134,169^ or Native American participants^120^; and 5 reported ~50% racial and/or ethnic minority groups.^113,130,133,167,174^ Forty-two articles reported data on SEP, most commonly as education or household income. The majority of studies reported participants across SEP groups, with roughly even distribution across the range of education and/or income levels. However, a smaller number of studies examined an exclusively higher SEP sample of health professionals and/or university graduates.^116–118,156,163,166,168,175^ No studies examined an exclusively lower-SEP population. Two articles included only participants with overweight or obesity.^115,138^ In general across this body of evidence, prevalence of overweight and obesity reflected U.S. population norms, and average BMI fell in the range of 23-27 kg/m^2^.

#### Intervention/exposure and comparator

As noted above, the intervention or exposure of interest for this systematic review question was SSB. Eligible comparators were consumption of different amounts of SSB (including no consumption and versions diluted with water), water, or LNCSB.

##### Randomized controlled trials

The trials examining SSB consumption tended to do so by enrolling habitual SSB consumers and randomizing them to SSB maintenance (typically as a non-beverage control group), LNCSB consumption,^122,131,142,143,149,154,170,173^ and/or water consumption.^122,131,143,149,154,170,173^ Only 2 trials did not have eligibility criteria around a minimum baseline SSB intake.^143,154^ Five trials provided beverages for all groups for the duration of the trial,^122,131,143,149,154^ while 2 provided the LNCSB and/or water only and treated the “SSB” group as a non-beverage-related control group with equal contact,^142,170^ and 1 did not provide any beverages but prescribed exclusive consumption of LNCSB, unsweetened beverages, or no change.^173^

Trial duration ranged from 12 weeks to 12 months, with most falling in the 12-week to 6-month range. Compliance was most commonly assessed using 24-hour recalls or returned beverage containers. Most trials aimed to study beverage impact on a broad set of outcomes beyond body composition and risk of obesity, including cardiometabolic risk factors, glycemia, cognition, and taste preference. Only 1 trial was explicitly a weight loss trial.^170^

##### Observational studies

The cohort studies in adults all examined varying amounts of SSB consumption as the exposure and comparator of interest with the exception of 1 article, which examined type of beverage consumed (SSB, LNCSB, or a combination of the two).^172^ The SSB definition varied considerably across articles, with some measurements limiting it to sugar-sweetened soft drinks, while others combined intake of soft drinks with fruit drinks, sweetened coffee or tea, lemonade, sports drinks, or fruit juice. One article explicitly included LNCSB in their measure of SSB,^128^ one article examined SSB intake only while watching TV,^127^ and 4 articles gave no definition beyond “sugar-sweetened beverages”.^112,115,138,174^

The large majority of articles utilized food frequency questionnaires to assess intake,^29,50,113,114,116–119,121,124,130,132,135–137,139–141,144,147,148,150–153,155,158–161,163–169,171,175^ though 13 articles used a short questionnaire,^115,123,127,128,133,134,138,145,146,156,162,172,174^ and a small number of studies used 24-hour dietary recalls,^112,125,126^ multiple day dietary records,^129,157^ or direct measurement.^120^ Twenty seven articles analyzed categorical SSB intake (e.g., quartiles),^29,112,116–119,123,126–128,132–134,136,137,144,145,147,151,153,159,161,166,167,171,172,174^ 23 looked at continuous intake,^50,113–115,120,124,125,129,130,138–141,146,148,150,156,158,160,162,164,165,168,175^ and a small number examined both.^121,135,152,155,157,163,169^ The metric of assessment varied greatly across studies (e.g., servings, ounces, milliliters, kilocalories).

#### Outcomes

##### Randomized controlled trials

All trials reported outcome measures of body composition (e.g., waist circumference, fat mass), and all but one trial^149^ also included risk of obesity measures (e.g., weight, BMI). Specifically, 6 articles measured body fat,^122,131,142,143,149,154^ either as absolute fat mass or percent body fat, and 4 measured waist circumference.^142,149,170,173^ Six of the 8 trials measured weight^122,131,142,143,154,170^ and 4 measured BMI.^122,142,143,173^

##### Observational studies

Measures of risk of obesity were more commonly studied in the cohort articles than measures of body composition, though a large proportion of the articles included outcomes in both categories. Forty-seven articles included risk of obesity measures (e.g., weight, BMI),^29,50,112,114–121,123–129,134,137–139,141,144–146,148,150–153,155–163,165,166,168,171,172,174,175^ and 21 articles included measures of body composition (e.g., waist circumference, percent body fat).^113,116,121,128–130,132,133,135,136,140,141,147,150,152,158,160,164,167,169,174^ The majority of studies utilized outcome data measured using validated methods; however, 19 articles relied at least partially on self-reported outcome data.^50,116–119,127,140,148,156,159–163,166,168,169,171,175^

#### Studies included in meta-analyses

Seven RCTs^122,131,142,143,154,170,173^ and 25 PCS^114,116,117,121,125,128,135,138–140,146,150–152,155,157,158,160,162,164,168,169,171,172,175^ provided usable data for meta-analysis. Articles were excluded from the meta-analysis because NESR analysts were unable to estimate an effect size,^115,118,120,129,133,141,149,153,159,165^ too few studies reported the particular exposure or outcome,^29,50,112,113,119,123,124,127,130,132,134,136,137,144,145,147,148,161,163,166,167,174^ or data overlapped with other included results.^118,126,156,166^

##### Randomized controlled trials

The population, interventions, and comparators for the RCTs were similar to the full body of evidence as all but one RCT^149^ were included in the meta-analysis. The outcomes with sufficient data to permit meta-analysis included change in weight, change in fat mass, and change in BMI over time.

##### Observational studies

Approximately 40% of the PCS included in the full body of evidence were not included in the meta-analysis. Of those that were included, the studies were most frequently conducted in the U.S. (7 articles).^114,125,128,138,168,172,175^ The remainder were conducted in Spain,^116,117,135,150^ Australia,^155,162,171^ Denmark,^140,160^ the Netherlands,^121,158^ Mexico,^139,169^ Belgium,^157^ Finland,^146^ Norway,^151^ and Singapore,^152^ and one additional article included cohorts from Italy, the UK, The Netherlands, Germany, Denmark.^164^ Analytic sample sizes and mean ages in the studies included in meta-analyses were similar to those for the full body of evidence. The meta-analysis evidence may have been less diverse than the full evidence, but most studies did not report data on race and/or ethnicity^116,117,121,135,139,140,146,151,155,157,158,160,164,171^ or on SEP.^128,140,151,157,164,169^ Of the articles that reported data on race and/or ethnicity, 8 reported predominately White participants^114,125,128,138,150,168,172,175^; 3 reported that 8-34% of participants were Black^114,125,138^; 1 reported all participants were Asian^152^; and 1 reported all participants were Hispanic.^169^ No studies specifically mentioned Native American participants. Of the articles that reported data on SEP, distributions were generally similar to those in the full body of evidence.

As in the full body of evidence, the articles included in the meta-analysis had heterogeneous definitions of SSB, and nearly all measured via food frequency questionnaires. Fourteen articles analyzed continuous SSB intake,^114,135,138–140,146,150,155,158,160,162,164,168,175^ 6 analyzed intake categorically,^116,117,128,151,171,172^ and 5 analyzed both.^121,125,152,157,169^

Nineteen articles measured change in weight,^114,116,117,121,125,138,139,146,150,152,155,157,158,160,162,168,169,172,175^ 9 measured waist circumference,^121,135,140,150,152,158,160,164,169^ and 5 measured risk of overweight or obesity.^116,128,135,151,171^ The majority of studies utilized outcome data measured using validated methods; however, 10 articles collected self-reported outcome data.^116,117,140,151,162,164,168,169,171,175^

### Synthesis of the evidence

Across the body of evidence, roughly two thirds of the studies found unfavorable associations with SSB consumption and at least one outcome of interest, and the remaining third of studies found exclusively null associations. Over half of the studies that found unfavorable associations showed a mix of unfavorable and null associations.

After examining the full body of evidence, the decision was made to synthesize the evidence separately for the body composition outcomes (e.g., waist circumference, percent fat mass, fat-free mass) and risk of obesity outcomes (e.g., weight, BMI, incidence of overweight or obesity). Furthermore, in addition to examining each full body of evidence, observational studies with repeat exposure assessment were compared to those with only baseline measurement to determine if that element of study quality affected the trend in results.

#### Body composition

##### Randomized controlled trials

All 8 RCTs examined at least one measure of body composition, though they varied substantially in which measures were assessed. Five trials found no effect of switching from habitual SSB intake to LNCSB or unsweetened beverages on body composition outcomes.^122,142,149,154,170^ Of the remaining 3 trials, one found those who consumed sucrose-sweetened beverages had greater increase in fat mass and fat-free mass over 12 weeks compared to those consuming LNCSB,^143^ one found greater increase in waist circumference and hip circumference over 6 months in the SSB group compared to the unsweetened beverages group, but no difference from the LNCSB group,^173^ and the third found no overall impact on fat mass but a greater increase in fat mass for SSB compared to LNCSB or unsweetened beverages for those at the highest tertile of baseline trunk fat.^131^

There were no notable differences in findings between trials of different durations, in those exclusively enrolling populations with overweight or obesity, or between trials enrolling habitual SSB consumers compared to those that did not require a minimum SSB intake at baseline. The majority of trials showed adequate compliance with beverage intake, though one reported no between-group differences in SSB across the trial,^149^ and a second did not report compliance data.^154^ Both trials with inadequate or missing compliance data found null effects on body composition outcomes.

##### Observational studies

Twenty-one prospective cohort studies examined at least one body composition outcome. Over half found an unfavorable association between SSB and at least one body composition outcome,^113,116,121,128,130,133,135,136,164,167,169,174^ while nine articles found no association.^129,132,140,141,147,150,152,158,160^ Results were similarly mixed regardless of whether the exposure was measured at baseline only or repeatedly. Most non-significant findings trended toward an unfavorable relationship.

#### Risk of obesity

##### Randomized controlled trials

Seven of the 8 trials examined risk of obesity outcomes, most commonly weight and BMI. Four trials found a significant effect of switching from habitual SSB intake to LNCSB or unsweetened beverages on risk of obesity. Specifically, one showed greater weight and BMI increases over 12 weeks in sucrose-sweetened beverages compared to LNCSB,^143^ one showed greater BMI increase in SSB compared to unsweetened beverages but not LNCSB,^173^ one showed no effect on weight but a greater likelihood of achieving 5% weight loss in the LNCSB group compared to SSB but not unsweetened beverages compared to SSB,^170^ and the fourth found no overall impact on weight but a greater increase in weight in SSB compared to LNCSB or unsweetened beverages for those at the highest tertile of baseline trunk fat.^131^

The two trials with notably smaller sample sizes both found null effects.^122,154^ No notable differences in findings were observed between trials of different durations, trials exclusively enrolling a population with overweight or obesity, or trials enrolling habitual SSB consumers compared to those that did not require a minimum SSB intake at baseline. The majority of trials showed adequate compliance with beverage intake, though one did not report compliance data and found no effect of beverage type on risk of obesity.^154^

##### Observational studies

Forty-seven prospective cohort studies examined at least one risk of obesity outcome. Over half found an unfavorable association between SSB and at least one risk of obesity outcome,^114–118,120,121,123,125,126,128,138,145,148,156,157,159–163,166,168,171,172,174,175^ while eighteen articles found no association,^29,50,112,119,124,127,129,137,139,141,144,146,150–153,155,158^ and 2 articles found a favorable association.^134,165^

Results were similarly mixed regardless of whether the exposure was measured at baseline only or repeatedly, though the two studies showing a favorable association between SSB intake and risk of obesity measured SSB intake at baseline only. Most non-significant findings trended toward unfavorable relationships.

#### Meta-analysis

Fifteen observations (i.e., effect sizes) from 12 articles^114,125,138,139,150,152,155,157,158,162,169,175^ of 200,343 adults were included in the meta-analysis to examine the relationship between change in SSB intake, measured continuously, and change in weight (Figure 4, Table 7, Figure A 59 through Figure A 66). For each additional 12 oz/d in SSB over time, weight increased by 0.55 (95% CI: 0.27, 0.83) kg on average. Heterogeneity, as measured by σ^2^, I^2^, and 95% PI, was high. The relationship did not differ by sex, TEI adjustment, whether juice was included in the exposure group, or whether results were self-reported, nor did the results vary substantially by age at exposure or by the time between exposure and outcome assessment.

Figure 4 Meta-analysis of change in SSB intake in adults (continuous, 12 oz/d) and change in weight (kg).*

* BMI: body mass index; CI: confidence interval; d: day; kg: kilogram; ML: multilevel; mo: month; oz: ounce; SSB: sugar-sweetened beverage

This figure shows a forest plot summarizing the meta-analysis of change in SSB (measured continuously, per 12 oz/d intake) and change in weight. This figure shows a forest plot summarizing the meta-analysis of change in SSB (measured continuously, per 12 oz/d intake) and change in weight in adults. Overall, weight increases by 0.55 (95% CI: 0.27, 0.83) kg in adults with each additional increase of 12 oz/d SSB.t in adults. Overall, weight increases by 0.55 (95% CI: 0.27, 0.83) kg in adults with each additional increase of 12 oz/d SSB.

Table 7 Summary of meta-analyses in adults

Exposure and outcome | Summary statistics for main analyses | Sample size
RCT
SSB intervention and change in weight | Pooled SMD: 0.21 (−0.06, 0.48), p=0.13, I^2^: 66.3%, 95% PI: −0.41, 0.83 | 12 observations from 6 articles, including 960 adults
SSB intervention and change in fat mass | Pooled SMD: 0.10 (−0.04, 0.25), p=0.17, I^2^: 0.0%, 95% PI: −0.04, 0.25 | 10 observations from 5 articles, including 462 adults
SSB intervention and change in BMI | Pooled SMD: 0.16 (0.01, 0.30), p=0.03, I^2^: 0%, 95% PI: 0.01, 0.30 | 8 observations from 4 articles, including 569 adults
PCS
Change in weight
Change in SSB (per 12 oz/d) and change in weight | Pooled slope: 0.55 (0.27, 0.83), <0.01, I^2^: 87.9%, 95% PI: −0.25, 1.35 | 15 observations from 12 articles, including 200,343 adults
Change in SSB (Increase/no change versus decrease) and change in weight | Pooled slope: 0.75 (0.40, 1.09), p<0.01, I^2^: 67.7%, 95% PI: 0.05, 1.44 | 12 observations from 4 articles, including 23,249 adults
SSB intake at baseline (per 12 oz/d) and change in weight | Pooled slope: 0.05 (0.01, 0.09), p=0.02, I^2^: 0.0%, 95% PI: 0.01, 0.09 | 4 observations from 4 articles, including 83,425 adults
SSB intake at baseline (Some versus less/none) and change in weight | Pooled slope: 0.82 (−0.07, 1.72), p=0.07, I^2^: 99.8%, 95% PI: −1.04, 2.69 | 10 observations from 4 articles, including 86,212 adults
Change in waist circumference
Change in SSB (per 12 oz/d) and change in waist circumference | Pooled slope: 0.38 (−0.06, 0.81), p=0.09, I^2^: 87.2%, 95% PI: −0.51, 1.26 | 4 observations from 4 articles, including 21,579 adults
SSB intake at baseline (per 12 oz/d) and change in waist circumference | Pooled slope: 0.09 (−0.00, 0.18), p=0.06, I^2^: 35.9%, 95% PI: −0.06, 0.25 | 6 observations from 5 articles, including 175,149 adults
Risk of obesity
SSB intake at baseline (More versus less/none) and risk of obesity | Pooled OR: 1.35 (1.16, 1.56), p<0.01, I^2^: 24.3%, 95% PI: 1.05, 1.73 | 10 observations from 5 articles, including 20,929 adults

When change in SSB was measured categorically the results were similar to those of the continuous SSB intake analysis: increasing intake or no change in intake over time versus decreasing intake over time was associated with an additional 0.75 (95% CI: 0.40, 1.09) kg over time. Heterogeneity, as measured by σ^2^, I^2^ and 95% PI, was moderate to high (Table 7, Figure A 67, Table A 15). SSB intake at baseline, analyzed continuously, was associated with increases in mean weight over time (Table 7, Figure A 69 through Figure A 74). When baseline SSB intake was analyzed categorically, the relationship with change in weight was not statistically significant, but the pooled slope suggested a trend of increasing mean weight with higher SSB intake (Table 7, Figure A 75, Table A 16). No interventions to reduce SSB significantly affected change in weight (Table 7, Figure A 77).

Too few studies were available for quantitative analyses of the risk of reporting bias (i.e., funnel plots or tests of funnel plot asymmetry) for continuous SSB intake at baseline and change in weight. For other meta-analyses of change in weight, funnel plot asymmetry analyses indicated that 1-3 studies may be missing from the analyses, and that publication bias could explain the asymmetry (Figure A 68, Figure A 76, Figure A 79). Further, true heterogeneity may also explain some of the asymmetry, as some of the subgroup analyses explained differences in effect sizes.

Change in SSB intake was not significantly associated with change in waist circumference, although the pooled slope combining 4 observations from 4 articles^150,152,158,169^ reflected greater increases in waist circumference with greater increases in intake (Table 7, Figure A 80 through Figure A 86). Higher SSB intake at baseline, analyzed categorically, was associated with a greater increase in waist circumference over time (Table 7, Figure A 87 through Figure A 92). When baseline SSB intake was analyzed continuously, the relationship with change in waist circumference was not statistically significant, but the pooled slope suggested a trend of greater increases in waist circumference with higher SSB intake. Too few studies were observed to complete quantitative analyses of the risk of reporting bias (i.e., funnel plots or tests of funnel plot asymmetry).

Higher SSB intake at baseline was associated with greater odds of overweight/obesity (Table 7, Figure A 93, Table A 17). Similarly, interventions to reduce SSB showed greater increases in BMI in the higher intake group (Table 7, Figure A 95, Figure A 96). For the PCS, funnel plot asymmetry analyses indicated that 1 study may be missing from the analyses (Figure A 94). Publication bias and/or true heterogeneity could explain the asymmetry, as some of the subgroup analyses explained differences in effect sizes. There was no evidence of non-reporting bias in the RCT analysis.

Interventions to reduce SSB did not have a statistically significant effect on change in fat mass (Table 7, Figure A 97, Figure A 98). A funnel plot asymmetry analysis indicated that no studies were missing from the meta-analysis, suggesting a lack of non-reporting bias (Figure A 99).

Due to the limited number of results in each exposure-outcome group, dose-response analyses were not conducted.

Study-by study influence analyses generally suggested consistent findings.

### Conclusion statements and grades

The 2025 Dietary Guidelines Advisory Committee developed and graded conclusion statements for the systematic review question: “What is the relationship between sugar-sweetened beverage consumption and growth, body composition, and risk of obesity?” based on review of the totality of evidence in adults (see Table 8 and Table 9).

Table 8 Conclusion statement and grade for sugar-sweetened beverage consumption and body composition in adults

Conclusion Statement | Sugar-sweetened beverage consumption by adults and older adults is associated with unfavorable body composition. This conclusion statement is based on evidence graded as moderate.
Grade | Moderate
Body of Evidence | 8 RCTs (7 in meta-analysis); 21 prospective cohort studies (9 in meta-analysis)
Consistency | Some concerns with consistency with a mix of null and unfavorable findings, and meta-analysis findings that were not statistically significant, but sometimes trended toward unfavorable associations
Precision | Some concerns with precision due to large confidence intervals and a small number of trials with very small sample sizes
Risk of bias | Some concerns with risk of bias, primarily due to confounding and missing data in observational studies
Directness | Few concerns with directness across studies
Generalizability | Some concerns with generalizability to the US population due to lack of diversity in race and/or ethnicity and socioeconomic position across the evidence, and age and weight status in the trials

#### Assessment of the evidence

The body of evidence underlying the conclusion statement above includes 8 RCTs (7 included in meta-analysis) and 21 observational studies (9 included in meta-analysis). The evidence was graded based on an assessment of 5 grading elements, as described below. In addition, publication bias was also a consideration; a funnel plot asymmetry analysis for RCTs examining change in fat mass indicated potential reporting bias. However, funnel plot analyses were not possible for the rest of the evidence on body composition due to the limited amount of evidence.

##### Consistency

Over half the studies examining body composition outcomes found a relationship between SSB consumption and at least one body composition outcome, though a substantial proportion of studies found no relationship. This heterogeneity in findings was shown in the RCT and PCS evidence. All significant findings indicated that SSB consumption was related to unfavorable body composition outcomes, and many non-significant findings trended in that direction. No studies found a relationship between SSB consumption and favorable body composition outcomes. The meta-analyses findings on change in waist circumference indicated a similar direction of relationship between higher SSB intake and increases in waist circumference, though pooled effect sizes were small, confidence intervals included zero, statistical power was limited, and moderate to high heterogeneity was found in many analyses.

##### Precision

Sample sizes varied considerably across studies, though most trials were adequately powered, and the vast majority of observational studies examined <1,000 participants. Two trials did not report power calculations and appeared to be underpowered. Meta-analyses included a reasonable number of participants, though some analyses included few studies or observations. Studies had a mix of reasonable or wide 95% confidence intervals.

##### Risk of bias

The primary sources of bias in RCTs were inadequate randomization methods and high attrition, though these issues affected only 2 of the 8 trials. Risk of bias was more pronounced in the observational studies, with many failing to adequately adjust for confounding or missing data.

##### Directness

Most trials were designed to test the effect of switching from SSB consumption to another beverage type, such as unsweetened beverages or LNCSB, on the outcomes of interest. The majority of observational studies examined the relationship of interest, and concerns with directness were minimal.

##### Generalizability

Generalizability was limited in this body of evidence, particularly in the trials. Less than half of the trials reported data on race and/or ethnicity or socioeconomic position, though those that did examined a majority of racial and/or ethnic minority participants. The trials primarily enrolled young adult female participants of higher socioeconomic position. Different racial and/or ethnic groups were better represented in the observational studies, though multiple studies did not provide that information. Diversity in socioeconomic position and age was also more common in the observational studies. Studies included in the meta-analysis were similar, in general, though they showed less racial and/or ethnic diversity.

Table 9 Conclusion statement and grade for sugar-sweetened beverage consumption and risk of obesity in adults

Conclusion Statement | Sugar-sweetened beverage consumption by adults and older adults is associated with higher risk of obesity. This conclusion statement is based on evidence graded as moderate.
Grade | Moderate
Body of Evidence | 7 RCTs (7 in meta-analysis); 47 prospective cohort studies (23 in meta-analysis)
Consistency | Some concerns with consistency with a mix of null and unfavorable findings, though null findings trended toward unfavorable associations; some statistically significant meta-analysis findings with consistency in direction, though magnitudes were small
Precision | Some concerns with precision due to large confidence intervals and several studies with very small sample sizes
Risk of bias | Some concerns with risk of bias, primarily due to confounding and missing data in observational studies
Directness | Few concerns with directness across studies
Generalizability | Some concerns with generalizability to the US population due to lack of diversity in race and/or ethnicity and socioeconomic position across the evidence and age and weight status in the trials

#### Assessment of the evidence

The body of evidence underlying the conclusion statement above includes 7 RCTs (all included in meta-analysis) and 47 observational studies (23 included in meta-analysis). The evidence was graded based on an assessment of 5 grading elements, as described below. In addition, publication bias was also a consideration and was assessed by funnel plot analyses. While non-reporting bias analysis was not possible for all meta-analyses, when they were possible, funnel plot asymmetry analyses suggested little or no potential publication bias in this body of evidence.

##### Consistency

Over half the studies examining risk of obesity outcomes found a relationship between SSB consumption and at least one outcome, though a substantial proportion of studies found no relationship. This heterogeneity in findings was shown in the RCT and PCS evidence. Most significant findings indicated that SSB consumption was related to higher risk of obesity, and many non-significant findings trended in that direction. Two studies found an association between SSB consumption and lower risk of obesity, though those studies measured intake at baseline only. The meta-analysis findings on change in weight and risk of overweight or obesity indicated a similar direction, with higher SSB intake relating to unfavorable outcomes, though effect size magnitudes were small, confidence intervals sometimes included zero, statistical power was limited, and moderate to high heterogeneity existed in many analyses.

##### Precision

Sample sizes varied considerably across studies, though most trials were adequately powered, and most observational studies examined <1,000 participants. Two trials did not report power calculations and appeared to be underpowered. Meta-analyses included a reasonable number of participants, though some analyses were based on few studies or observations. Studies had a mix of reasonable or wide 95% confidence intervals.

##### Risk of bias

In general, risk of bias was low in the trials and more substantial in the observational studies. One trial failed to provide adequate randomization methods. The observational studies commonly did not adequately adjust for confounding or missing data, and issues around exposure measurement were also noted for small number of studies.

##### Directness

Most trials were designed to test the effect of switching from SSB consumption to another beverage type, such as unsweetened beverages or LNCSB, on the outcomes of interest. The majority of observational studies examined the relationship of interest, and concerns with directness were minimal.

##### Generalizability

Generalizability was limited in this body of evidence, particularly in the trials. Less than half of the trials reported data on race and/or ethnicity or socioeconomic position, though those that did examined a majority of racial and/or ethnic minority participants. The trials primarily enrolled young adult female participants of higher socioeconomic position. The observational studies had greater representation of different racial and/or ethnic groups, though multiple studies did not provide that information. Diversity in socioeconomic position and age was also more common in the observational studies. Studies included in the meta-analysis were similar, in general, though they showed less racial and/or ethnic diversity than the full body of evidence in the systematic review.

## Individuals during pregnancy and postpartum

### Description of the evidence

The body of evidence examining the relationship between SSB consumption and gestational weight gain and postpartum weight change included 11 articles. These articles are summarized in Table 18 (individuals during pregnancy) and Table 19 (individuals during postpartum). Risk of bias assessments for articles in these populations are provided in Table 20 (individuals during pregnancy) and Table 21 (individuals during postpartum).

#### Population

The 11 articles in individuals during pregnancy and postpartum reported on 11 prospective cohort studies. Five countries were represented in the included articles, with 7 articles coming from the U.S.^176,177,182–186^ and 1 each from Denmark,^180^ Iceland,^179^ Mexico,^181^ and Singapore.^178^ Two articles^178,183^ reported receiving industry funding; funding sources for all articles are reported in Table 18 and Table 19.

##### Individuals during pregnancy

In the 7 articles assessing the relationship between SSB consumption and gestational weight gain (GWG) during pregnancy, sample sizes ranged from N=111 to N=1,388 participants. One article included only adolescents during pregnancy;^181^ all others were in adult populations with mean ages from late twenties to early thirties. Renault et al^180^ included only women who had obesity (BMI ≥30 kg/m^2^) pre-pregnancy, while others did not have inclusion/exclusion criteria based on weight. Four of the 7 articles reported race and/or ethnicity data. Of these, 2 articles were from studies in predominantly White populations,^179,182^ 1 article reported that >50% of participants were from racial and/or ethnic minority groups,^176^ and 1 article included Asian women of Chinese, Malay, or Indian ethnicity.^178^ Four articles reported information on SEP; two of these were in lower-SEP populations^176,181^ and 2 articles included a range of income and education levels.^177,178^

##### Individuals during postpartum

Four articles assessed the relationship between SSB consumption and postpartum weight change (PPWC); all were conducted in the U.S. Sample sizes ranged from N=58 to N=888 participants and mean age of participants was 32.2 years. Cahill et al^184^ included only individuals with BMI ≥25 kg/m^2^ and Davis et al^185^ included only individuals with a history of gestational diabetes. All articles included race and/or ethnicity data, and all participant populations were <50% White. Three articles reported information on SEP, including a range of education and income levels.

#### Intervention/exposure and comparator

The intervention or exposure of interest for this systematic review question was SSB. Eligible comparators were consumption of different amounts of SSB (including no consumption and versions diluted with water), water, or LNCSB.

##### Individuals during pregnancy

All 7 articles examined varying levels of SSB intake as their exposure and comparator of interest. The definitions of SSB varied across articles, with one including only sugar-sweetened, carbonated soft drinks^180^ and others including a broader range of beverages (e.g., fruit drinks, sports drinks, and sweetened tea and coffee). Four articles used food frequency questionnaires to assess SSB intake, while 2 articles used lifestyle questionnaires and 1 used dietary recalls. Three articles compared SSB intake dichotomously (e.g., any intake versus none, < once per day versus ≥ once per day), two compared intake categorically (e.g., across tertiles of SSB servings per week); and 2 articles continuously compared different intake levels of SSB. The units used to measure SSB intake varied across articles (e.g., frequency, servings, grams), though the time scales for consumption consistently measured daily intake.

Six of the 7 articles used a single estimate of SSB intake: 2 of these articles measured intake during the first trimester,^176,180^ 3 articles measured intake in the second or third trimester,^177,178,181^ and 1 article used the mean of SSB intake assessed in the first and second trimesters.^182^ Olafsdottir et al^179^ measured SSB intake from 11-15 weeks gestation and 34-37 weeks gestation to estimate change in intake throughout pregnancy in relation to GWG.

##### Individuals during postpartum

All articles in postpartum populations examined varying levels of SSB intake as their exposure and comparator of interest. As in the articles examining individuals during pregnancy, the definition of SSB varied across articles: 1 article included only regular soda, 1 article included only fruit juice (unable to confirm that it was 100% juice), and 2 articles included a broad range of sweetened beverage types. The 4 articles varied with respect to exposure assessment tools and timing of exposure assessment:

- Alderete et al^183^ measured SSB intake with 24-hour dietary recalls at 1-month and 6-months postpartum and analyzed PPWC at 6 months by change in SSB intake.
- Cahill et al^184^ used a validated FFQ to measure fruit juice intake at baseline (week 1) and week 10, and analyzed PPWC at 10 weeks by change in fruit juice intake.
- Davis et al^185^ measured soda intake at one time point (6-9 weeks postpartum) using a questionnaire and analyzed PPWC at 1 year.
- Mahabamunuge et al^186^ measured SSB intake at one time point (between 2 weeks and 4 months postpartum) using a validated dietary survey; PPWC was assessed at 6 months (± 8 weeks).

Three articles compared SSB intake continuously and 1 article^185^ compared different categories of intake levels of SSB (none, <1 12-fluid ounce serving/week, ≥2 servings/week).

#### Outcomes

##### Individuals during pregnancy

Studies that assessed adequacy of total GWG (i.e., in relation to recommendations based on pre-pregnancy BMI) were included in this body of evidence. Studies were excluded if they examined GWG only during certain time periods or trimesters of pregnancy or if they did not examine absolute total GWG in relation to recommendations based on pre-pregnancy BMI.

Four articles included self-reported pre-pregnancy weight to calculate GWG;^178,180–182^ the remaining 3 articles had baseline weight measured by clinical or study staff during the first trimester.^176,177,179^ Most studies classified GWG as inadequate, adequate, or excessive according to the Institute of Medicine (2009) guidelines,^*^ with the exception of Olafsdottir et al^179^ which used Icelandic guidelines. Three articles assessing GWG adjusted for TEI.

* Institute of Medicine (US) and National Research Council (US) Committee to Reexamine IOM Pregnancy Weight Guidelines. Weight Gain During Pregnancy: Reexamining the Guidelines. (Rasmussen KM, Yaktine AL, eds.). Washington (DC): National Academies Press (US); 2009

##### Individuals during postpartum

PPWC was assessed at different time points using a range of methods across the included studies:

- Alderete et al^183^ assessed PPWC as the difference in weights measured by investigators at baseline (1-month postpartum) and 6-months postpartum. This was the only article that adjusted for TEI.
- Cahill et al^184^ assessed PPWC as the difference in weights measured by investigators at baseline (week 1, unclear how many weeks postpartum participants were at baseline) and week 10.
- Davis et al^185^ assessed PPWC as the change between self-reported pre-pregnancy weight and clinically measured weight at 1-year postpartum. Substantial postpartum weight retention (SPWR) was defined as retaining ≥5kg at 1-year postpartum, as compared with pre-pregnancy weight.
- Mahabamunuge et al^186^ assessed PPWC as the difference between pre-pregnancy weight (from electronic health records) and clinically measured weight at 6 months postpartum. SPWR was defined as an increase from pre-pregnancy weight of ≥5kg at 6 months postpartum.

### Synthesis of the evidence

Since energy intake is an important covariate when interpreting studies on the relationship between SSB consumption and both GWG and PPWC, whether or not articles adjusted for TEI was considered within the evidence syntheses.

#### Individuals during pregnancy

Most articles (4 of 7) reported only null associations between SSB consumption and GWG.^176,178,179,182^ Two articles reported direct (i.e., unfavorable) associations: Samano et al^181^ found higher risks of both excessive and insufficient GWG for Mexican adolescents who consumed any SSB versus those who consumed no SSB. Guilloty et al^177^ found an association between fruit drink consumption and GWG in their total sample, though no statistically significant associations for soft drinks and GWG were found in either the total sample or when soft drink or fruit drink intake was stratified by pre-pregnancy BMI. In a population that had pre-pregnancy overweight or obesity, Renault et al^180^ found a lower risk of excessive GWG when consuming <1 SSB per day compared to no SSB, though consuming ≥1 SSB per day was not associated with excessive GWG. The only article that measured change in SSB intake over the follow-up period did not report detailed results, stating only that the relationship between energy-providing drink consumption during pregnancy and GWG was not significant.^179^

#### Individuals during postpartum

Two of the 4 articles assessing PPWC found direct associations between SSB intake during postpartum and increased PPWC. Alderete et al^183^ found that PPWC increased from 1 to 6 months postpartum for 4-ounce per day increase in sweet soft drinks (b=1.46, 95% CI: 0.57, 2.35), sugary beverages excluding juice (b=0.70, 95% CI: 0.07, 1.33), and sugary beverages excluding juice and dairy (b=0.69, 95% CI: 0.06, 1.32). Mahabamunuge et al^186^ also found an association between SSB intake (measured at 1 month postpartum) and postpartum weight retention at 6 months; however, the association with substantial postpartum weight retention (≥5 kg) was not statistically significant. In a sample of postpartum women with a history of gestational diabetes mellitus, a relationship between consuming ≥2 servings of SSB per week and postpartum weight retention ≥5 kg at 1 year was moderate in size but still outside the range of statistical significance (odds ratio (95% CI): 1.61 (0.98, 2.66), p=0.06). Cahill et al^184^ found no association between change in fruit juice intake (not specified as 100% juice) and PPWC over 10 weeks in postpartum women with overweight or obesity.

#### Summary

There were serious concerns with consistency across exposure and outcome assessments within the evidence base for individuals during pregnancy, including: the exposure was measured at different time points in pregnancy using different assessment methods, the outcome was measured at different time points, time frames for gestational weight gain varied between studies, there was variation between studies in the analytic approach, most studies did not take into account gestational age, and some studies adjusted for TEI while others did not. These concerns with consistency precluded any ability to discern the relevance of findings to the U.S. population. There was a small number of articles with relatively small sample sizes. This led to concerns about being underpowered to detect associations, particularly for adequacy of gestational weight gain. All articles were assessed as having a high risk of bias in at least one domain, most commonly for not accounting for key confounders, exposure misclassification, and not accounting for missing data. Studies assessed multiple dietary exposures and were not designed to specifically assess the relationship between SSB intake and gestational weight gain. In several cases, the definition of gestational weight gain was poorly defined.

Only 4 articles assessed the relationship between SSB and postpartum weight change; they showed little consistency in exposure definition, exposure assessment timing and method, and duration of follow-up. Like the evidence base in individuals during pregnancy, all articles in individuals during postpartum were assessed as having a high risk of bias in at least one domain. Only one article was designed to specifically assess the relationship of interest.

### Conclusion statements and grades

The 2025 Dietary Guidelines Advisory Committee developed conclusion statements for the systematic review question: “What is the relationship between sugar-sweetened beverage consumption and growth, body composition, and risk of obesity?” based on review of the totality of evidence in individuals during pregnancy (Table 10) and individuals during postpartum (Table 11). Publication bias was also a consideration; however, it was not deemed a serious concern for these bodies of evidence because multiple studies reported only nonsignificant findings while others reported significant findings or a mix of significant and nonsignificant findings. Conclusion statements could not be drawn for individuals during pregnancy and postpartum.

Table 10 Conclusion statement and grade for sugar-sweetened beverage consumption during pregnancy and gestational weight gain

Conclusion Statement | A conclusion statement cannot be drawn about the relationship between sugar-sweetened beverage consumption during pregnancy and adequacy of gestational weight gain because there is not enough evidence available, and there are substantial concerns with consistency, precision, risk of bias, directness, and generalizability in the available body of evidence.
Grade | Grade Not Assignable
Body of Evidence | 7 articles from prospective cohort studies
Rationale | The most serious concerns were with consistency, specifically with the assessment methods and timing for both the exposure and outcome, and with the definition of gestational weight gain within studies. The articles had relatively small sample sizes and thus underpowered studies. All articles had high risk of bias in at least one domain. All studies assessed multiple dietary exposures and were not specifically designed to analyze the relationship between SSB and gestational weight gain. Concerns with these elements precluded any ability to discern relevance of findings to the U.S. population.

Table 11 Conclusion statement and grade for sugar-sweetened beverage consumption during postpartum and postpartum weight change

Conclusion Statement | A conclusion statement cannot be drawn about the relationship between sugar-sweetened beverage consumption during postpartum and postpartum weight change because there is not enough evidence available.
Grade | Grade Not Assignable
Body of Evidence | 4 articles from prospective cohort studies
Rationale | Only 4 articles were in this evidence base; they showed little consistency in exposure definition, exposure assessment timing and method, and duration of follow-up.