# Methods

The Committee used NESR’s methodology to conduct this systematic review. NESR’s methodology is described in detail in its methodology manual,^*^ as well as in the Committee’s Scientific Report.^†^ This section presents an overview of the specific methods used to answer the systematic review question: What is the relationship between sugar-sweetened beverage consumption and growth, body composition, and risk of obesity?

* USDA Nutrition Evidence Systematic Review Branch. USDA Nutrition Evidence Systematic Review: Methodology Manual. February 2023. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: https://nesr.usda.gov/methodology-overview

† 2025 Dietary Guidelines Advisory Committee. 2024. Scientific Report of the 2025 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Health and Human Services and Secretary of Agriculture. U.S. Department of Health and Human Services. 10.52570/DGAC2025

This systematic review is an update to an existing NESR systematic review completed by the 2020 Dietary Guidelines Advisory Committee,^‡^ which included evidence published from January 2000 to June 2019. This update synthesized all of the eligible studies from January 2000 to May 2023 to develop and grade conclusion statements according to the methods described below. This means that all of the eligible articles from the existing review and the newly published articles were re-synthesized as one body of evidence.

‡ Mayer-Davis E, Leidy H, Mattes R, . Beverage Consumption and Growth, Size, Body Composition, and Risk of Overweight and Obesity: A Systematic Review. July 2020. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: 10.52570/NESR.DGAC2020.SR0401

In addition, this review is related to another systematic review conducted by the 2025 Committee to answer the scientific question: “What is the relationship between complementary feeding and growth, body composition, and risk of obesity?”^§^ That review examined complementary foods and beverages, including sugar-sweetened beverages (SSB), consumed by infants and young children up to age 24 months. Articles in infant and young children populations are included in this report in the context of the overall review of evidence from infancy through adolescence.

§ Fisher JO, Abrams SA, Andres A, . Complementary Feeding and Growth, Body Composition, and Risk of Obesity: A Systematic Review. November 2024. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: 10.52570/NESR.DGAC2025.SR18

## Develop a protocol

A systematic review protocol is the plan for how NESR’s methodology will be used to conduct a specific systematic review and is established by the Committee, a priori, before any evidence is reviewed. The protocol is designed to capture the most appropriate and relevant body of evidence to answer the systematic review question. Development of the protocol involves discussion of the strengths and limitations of various methodological approaches relevant to the question, which then informs subsequent steps of the systematic review process. The protocol describes all of the methods that will be used throughout the systematic review process. Additionally, the protocol includes the following components, which are tailored to each systematic review question: the analytic framework, the inclusion and exclusion criteria, and the synthesis plan. The Committee used the analytic framework and the inclusion and exclusion criteria from the existing 2020 review and made adjustments to the protocol, as needed. Differences in the inclusion and exclusion criteria between existing and updated reviews are documented in Appendix 3.

The protocol was posted online (https://nesr.usda.gov/protocols) for the public to view and comment on. Revisions to the systematic review protocol were made during the review process. These amendments are documented in Table 2.

Table 2 Protocol revisions

Date | Protocol revision | Description
July 2023 | The inclusion and exclusion criteria for the outcome of gestational weight gain were revised to include only those studies that examine adequacy of total gestational weight gain (i.e., in relation to recommendations based on pre-pregnancy BMI). Studies that examine gestational weight gain during certain time periods or trimesters of pregnancy or total gestational weight gain not in relation to recommendations will be excluded. | This revision was made to focus on the most clinically meaningful measure of gestational weight gain. The revision was made before evidence synthesis.
September 2023 | The inclusion criteria for study duration for weight loss and weight loss maintenance were reduced from ≥6 months and 12 months, respectively, to ≥12 weeks. | This revision was made so that study duration criteria are consistent across all growth, body composition, and risk of obesity outcomes. Longer-term studies on weight loss and weight loss maintenance will be prioritized in evidence synthesis. The revision was made before evidence synthesis.
September 2023 | The exclusion criteria for outcomes were revised to specify that studies that only report unintentional weight loss (i.e., a component of frailty) will be excluded. | This revision was made to clarify the intent of the outcome criteria but does not represent a change in how the criteria were applied. The revision was made before evidence synthesis.
December 2023 | The quantitative synthesis was updated to clarify the number of studies required to consider conducting a meta-analysis. | This revision was made to clarify that two studies are necessary, but not necessarily sufficient, to conduct a meta-analysis.

## Develop an analytic framework

An analytic framework visually represents the overall scope of the systematic review question and depicts the contributing elements that were examined and evaluated. It presents the core elements of each systematic review question, including the Population (i.e., those who experience the intervention/exposure and/or outcome), Intervention and/or exposure (i.e., the independent variable of interest), Comparator (i.e., the alternative being compared to the intervention or exposure), and Outcome(s). The Committee identified key confounders based on their knowledge of nutrition and health research and experience as subject matter experts. Key confounders are participant characteristics, health status, demographics, diet and lifestyle behaviors, and/or other factors related to both the intervention/exposure and the outcome of interest that may impact the relationships of interest. Key confounders were considered during review and evaluation of the evidence, particularly during the risk of bias assessment of non-randomized and observational studies.

Figure 1 is the analytic framework for the systematic review and shows that the intervention or exposure of interest is sugar-sweetened beverage (SSB) consumption in infants, young children, children, adolescents, adults, older adults, and individuals during pregnancy and postpartum. The comparators are consumption of a different amount of SSB (including no consumption and versions diluted with water), SSB versus water, and SSB versus low- and no-calorie sweetened beverages. The outcomes are Growth (in infants, young children, children, adolescents) including: height, length/stature-for-age, weight, weight-for-age, stunting, failure to thrive, wasting, BMI-for-age, weight-for-length/stature, body circumferences (arm, neck, thigh), head circumference; Body composition (in infants, young children, children, adolescents, adults, older adults) including: skinfold thickness, fat mass, ectopic fat, fat-free mass or lean mass, waist circumference, waist-to-hip-ratio; Risk of obesity (in children, adolescents, adults, older adults) including: BMI, underweight, normal weight, overweight and/or obesity, weight loss and maintenance (in adults and older adults); Pregnancy and postpartum-related weight change (in individuals during pregnancy or postpartum) including: gestational weight gain and postpartum weight change. The key confounders may impact the relationships of interest and are race and/or ethnicity, socioeconomic position, and anthropometry at baseline (all populations); sex (infants, young children, children, adolescents, adults, older adults); age, physical activity, and diet quality (children, adolescents, adults, older adults, pregnancy, postpartum); smoking (adults, older adults, pregnancy, postpartum); milk feeding practices (human milk, infant formula, or both), birth size, and gestational age (infants and young children); parity (pregnancy, postpartum), diabetes mellitus in the current pregnancy (pregnancy), hypertensive disorders in the current pregnancy (pregnancy), and human milk feeding (postpartum).

Figure 1 Analytic framework for the systematic review question: What is the relationship between sugar-sweetened beverage consumption and growth, body composition, and risk of obesity?

Population | Intervention/exposure | Comparator | Outcome | Key confounders
Infants and young children (birth up to 24 months) | Sugar-sweetened beverage (SSB) consumption | Consumption of different amounts of SSB (including no consumption and versions diluted with water); SSB versus. water; SSB versus. low- and no-calorie sweetened beverages | Growth (in infants, young children, children, adolescents); - Height, length/stature-for-age; - Weight, weight-for-age; - Stunting, failure to thrive, wasting; - BMI-for-age, weight-for-length/stature; - Body circumferences (arm, neck, thigh); - Head circumference; Body composition (in infants, young children, children, adolescents, adults, older adults); - Skinfold thickness; - Fat mass, ectopic fat; - Fat-free mass or lean mass; - Waist circumference, waist-to-hip-ratio; Risk of obesity (in children, adolescents, adults, older adults); - BMI; - Underweight; - Normal weight; - Overweight and/or obesity; - Weight gain; - Weight loss and maintenance (in adults, older adults) | - Sex; - Race and/or ethnicity; - Socioeconomic position; - Anthropometry at baseline; - Milk feeding practices (human milk, infant formula, or both); - Gestational age
Children and adolescents (2 years up to 19 years) | Sugar-sweetened beverage (SSB) consumption | Consumption of different amounts of SSB (including no consumption and versions diluted with water); SSB versus. water; SSB versus. low- and no-calorie sweetened beverages | | - Sex; - Age; - Race and/or ethnicity; - Socioeconomic position; - Anthropometry at baseline; - Physical activity; - Diet quality
Adults and older adults (19 years and older) | Sugar-sweetened beverage (SSB) consumption | Consumption of different amounts of SSB (including no consumption and versions diluted with water); SSB versus. water; SSB versus. low- and no-calorie sweetened beverages | | - Sex; - Age; - Race and/or ethnicity; - Socioeconomic position; - Anthropometry at baseline; - Physical activity; - Diet quality; - Smoking
Individuals during pregnancy and postpartum | Sugar-sweetened beverage (SSB) consumption | Consumption of different amounts of SSB (including no consumption and versions diluted with water); SSB versus. water; SSB versus. low- and no-calorie sweetened beverages | Pregnancy and postpartum-related weight change (in individuals during pregnancy or postpartum); - Gestational weight gain; - Postpartum weight change | - Age; - Race and/or ethnicity; - Socioeconomic position; - Anthropometry at baseline; - Physical activity; - Diet quality; - Smoking; - Parity; - Diabetes mellitus in the current pregnancy (pregnancy); - Hypertensive disorders in the current pregnancy (pregnancy); - Human milk feeding (postpartum)

Synthesis organization:

I. Population: Infants and young children; Children and adolescents; Adults; Older adults; Individuals during pregnancy; Individuals during postpartum
  a. Outcome: Growth; Body composition; Risk of obesity; Weight loss and maintenance; Pregnancy and postpartum-related weight change

## Develop inclusion and exclusion criteria

The inclusion and exclusion criteria provide an objective, consistent, and transparent framework for determining which articles to include in the systematic review (Table 3). These criteria ensure that the most relevant and appropriate body of evidence is identified for the systematic review question, and that the evidence reviewed is:^*^

- Applicable to the U.S. population of interest
- Relevant to Federal public health nutrition policies and programs
- Rigorous from a scientific perspective

* USDA Nutrition Evidence Systematic Review Branch. USDA Nutrition Evidence Systematic Review: Methodology Manual. February 2023. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: https://nesr.usda.gov/methodology-overview

Table 3 Inclusion and exclusion criteria

Category | Inclusion Criteria | Exclusion Criteria
Study design | - Randomized controlled trials; - Non-randomized controlled trials^†^; † Including quasi-experimental and controlled before-and-after studies; - Prospective cohort studies; - Retrospective cohort studies; - Nested case-control studies; - Mendelian randomization studies | - Uncontrolled trials^‡^; ‡ Including uncontrolled before-and-after studies; - Case-control studies; - Cross-sectional studies; - Ecological studies; - Narrative reviews; - Systematic reviews; - Meta-analyses; - Modeling and simulation studies
Publication date | - January 2000 – May 2023^§^; § This review update date range encompasses the original systematic review date range, which included articles published from January 2012 to June 2019 | - Before January 2000, after May 2023
Population: Study participants | - Human | - Non-human
Population: Life stage | - At intervention or exposure and outcome:; - Infants and young children (up to 24 months); - Children and adolescents (2 up to 19 years); - Adults and older adults (19 years and older); - Individuals during pregnancy; - Individuals during postpartum | - At intervention or exposure and outcome:; - N/A
Population: Health status | - Studies that [underlined: exclusively] enroll participants not diagnosed with a disease^*^; * Studies that enroll participants who are at risk for chronic disease were included; - Studies that enroll [underlined: some] participants:; - diagnosed with a disease;; - diagnosed with a disorder that affects feeding/eating or growth (e.g., autism spectrum disorder, attention-deficit/hyperactivity disorder, eating disorder);; - with severe undernutrition, failure to thrive/underweight, stunting, or wasting;; - born preterm,^†^ with low birth weight,^‡^ and/or small for gestational age;; † Gestational age <37 weeks and 0/7 days; ‡ Birth weight <2500g; - who became pregnant using Assisted Reproductive Technologies;; - with multiple gestation pregnancies;; - receiving pharmacotherapy to treat obesity;; - pre-or post-bariatric surgery;; - and/or hospitalized for an illness, injury, or surgery | - Studies that [underlined: exclusively] enroll participants:; - diagnosed with a disease;^§^; § Studies that exclusively enroll participants with obesity were included; - diagnosed with a disorder that affects feeding/eating or growth (e.g., autism spectrum disorder, attention-deficit/hyperactivity disorder, eating disorder);; - with severe undernutrition, failure to thrive/underweight, stunting, or wasting;; - born preterm,^†^ with low birth weight,^‡^ and/or small for gestational age;; - who became pregnant using Assisted Reproductive Technologies;; - with multiple gestation pregnancies;; - receiving pharmacotherapy to treat obesity;; - pre-or post-bariatric surgery;; - and/or hospitalized for an illness, injury, or surgery^**^; ** Studies that exclusively enroll participants post-cesarean section were included
Intervention/exposure | - SSB consumption; - Multi-component intervention in which the isolated effect of the intervention of interest on the outcome(s) of interest is provided or can be determined despite multiple components | - Infant milk, infant formula, toddler formula/milks; - Other beverage types, such as nutritional beverages (e.g., protein shakes, smoothies); - Studies focusing on specific nutrients added to beverages instead of a beverage as a whole (i.e., studies where beverages are the delivery mechanism for a nutrient); - Beverages that are not commercially available (e.g., experimentally manipulated beverages); - Supplements; - Alcohol; - Soups; - Multi-component intervention in which the isolated effect of the intervention of interest on the outcome(s) of interest is not provided or cannot be determined due to multiple components
Comparator | - Consumption of a different amount of SSB (including no consumption and versions diluted with water); - SSB versus water; - SSB versus low- and no-calorie sweetened beverages | - No comparator
Outcome(s) | Growth (in infants, young children, children, adolescents); - Height, length/stature-for-age; - Weight, weight-for-age; - Stunting, failure to thrive, wasting; - BMI-for-age, weight-for-length/stature; - Body circumferences (arm, neck, thigh); - Head circumference; Body composition (in infants, young children, children, adolescents, adults, older adults); - Skinfold thickness; - Fat mass, ectopic fat; - Fat-free mass, lean mass; - Waist circumference, waist-to-hip ratio; Risk of obesity (in children, adolescents, adults, older adults); - BMI; - Underweight; - Normal weight; - Overweight and/or obesity; - Weight gain; - Weight loss and maintenance (in adults, older adults); Pregnancy- and postpartum-related weight change (individuals during pregnancy or postpartum); - Adequacy of total gestational weight gain (i.e., in relation to recommendations based on pre-pregnancy BMI); - Postpartum weight change | - Gestational weight gain only during certain time periods or trimesters of pregnancy; - Absolute total gestational weight gain (i.e., not in relation to recommendations based on pre-pregnancy BMI); - Weight loss that is specifically classified as unintentional weight loss (e.g., a component of frailty)
Study duration | - Intervention length ≥12 weeks (in children, adolescents, adults, and older adults only) | - Intervention length <12 weeks (in children, adolescents, adults, and older adults only)
Publication status | - Peer-reviewed articles published in research journals | - Non-peer-reviewed articles, unpublished data or manuscripts, pre-prints, reports, editorials, retracted articles, and conference abstracts or proceedings
Language | - Published in English | - Not published in English
Country^*^; * The classification of countries on the Human Development Index (HDI) is based on the UN Development Program Human Development Report Office (http://hdr.undp.org/en/data) for the year the study intervention occurred or data were collected. If the study does not report the year(s) in which the intervention/exposure data were collected, the HDI classification for the year of publication is applied. Studies conducted prior to 1990 are classified based on 1990 HDI classifications. If the year is more recent than the available HDI values, then the most recent HDI classifications are used. If a country is not listed in the HDI, then the current country classification from the World Bank is used (The World Bank Country and Lending Groups, available from: https://datahelpdesk.worldbank.org/knowledgebase/articles/906519-world-country-and-lending-groups) | - Studies conducted in countries classified as high or very high on the Human Development Index the year(s) the intervention/exposure data were collected | - Studies conducted in countries classified as medium or low on the Human Development Index the year(s) the intervention/exposure data were collected

## Search for and screen studies

NESR librarians, in collaboration with NESR analysts and the Committee, used the analytic framework and inclusion and exclusion criteria to develop a comprehensive literature search strategy. The literature search strategy included selecting and searching the appropriate bibliographic databases, translating the search using syntax appropriate for the databases being searched, and employing search refinements, such as search filters. For existing reviews, search strategies were updated, as appropriate, for each database. The full literature search is documented in Appendix 4.

The results of all electronic database searches, after removal of duplicates, were screened independently by 2 NESR analysts using a step-wise process by reviewing titles, abstracts, and full-texts to determine which articles meet the inclusion criteria. Manual searching was conducted to find peer-reviewed published articles not identified through the electronic database search. These articles were also screened independently by 2 NESR analysts at the abstract and full-text levels.

To avoid duplication of efforts, studies including infants and young children were identified as part of another systematic review answering the systematic review question: What is the relationship between complementary feeding and growth, body composition, and risk obesity?^*^

* Fisher JO, Abrams SA, Andres A, Byrd-Bredbenner C, Deierlein A, Eicher-Miller HA, Odoms-Young A, Palacios C, Obbagy J, Bahnfleth C, Kim JH, Nevins J, Higgins M, Bokay K, Butera G, Terry N. Complementary Feeding and Growth, Body Composition, and Risk of Obesity: A Systematic Review Protocol. May 2023. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: https://nesr.usda.gov/protocols

## Extract data and assess the risk of bias

NESR analysts extracted all essential data from each included article to describe key characteristics of the available evidence, such as the author, publication year, cohort/trial name, study design, population life stage at intervention/exposure and outcome, intervention/exposure and outcome assessment methods, and outcomes. One NESR analyst extracted the data and a second NESR analyst reviewed the extracted data for accuracy. Each article included in the systematic review underwent a formal risk of bias assessment, with 2 NESR analysts independently completing the risk of bias assessment using the tool that is appropriate for the study design.^†^,^‡^,^§^

† Sterne JAC, Savović J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ 2019; 366: l4898.doi: 10.1136/bmj.l4898 31462531

‡ Sterne JAC, Hernán MA, Reeves BC, . ROBINS-I: a tool for assessing risk of bias in non-randomized studies of interventions. BMJ 2016; 355; i4919. doi: 10.1136/bmj.i4919 27733354

§ Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24). doi: 10.1016/j.envint.2024.108602.

## Synthesize the evidence

The Committee described, compared, and combined the evidence from all included studies to answer the systematic review question.^**^ Synthesis of the body of evidence involved identifying overarching themes or key concepts from the findings, identifying and explaining similarities and differences between studies, and determining whether certain factors impact the relationships being examined, which includes potential causes of heterogeneity across all included evidence. While the Committee considered the conclusion statement and grade from the existing review at the outset of synthesis discussions, they ultimately developed and graded conclusion statements based on a thorough evaluation of all included evidence (i.e., studies from the existing review and the newly published studies).

** USDA Nutrition Evidence Systematic Review Branch. USDA Nutrition Evidence Systematic Review: Methodology Manual. February 2023. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: https://nesr.usda.gov/methodology-overview

Extracted data and risk of bias assessments for all included studies were tabulated to visually display results and facilitate synthesis. During synthesis, the Committee considered the effect direction, magnitude, and statistical significance of the results reported across the articles included in the body of evidence. The evidence was synthesized qualitatively without meta-analysis of effect estimates, statistical pooling or conversion of data, or quantitative tests of heterogeneity, and quantitatively (see Quantitative synthesis plan).

The synthesis plan for this review was designed with the end-use in mind, to inform the Committee’s advice to HHS and USDA regarding dietary guidance across life stages. The first level of synthesis organization was by population. Then, within each of the population groups, the evidence was organized by similar outcome based on the available evidence. The Committee examined evidence from infancy through adolescence together in this report. Details from articles in infant and young children populations are provided in this report in the context of the overall review of evidence from infancy through adolescence.

### Quantitative synthesis plan

The primary objective of the quantitative synthesis (i.e., meta-analysis) was to estimate the average effects of the consumption of SSB by infants, young children, children, adolescents, adults, and older adults on growth, body composition, and risk of obesity (GBCO), along with the precision of those averages. Further, the meta-analysis explored whether the association between the consumption of SSB and GBCO varied across population subgroups (e.g., by age and weight status at intervention/exposure), and whether differences in other study-specific variables (e.g., whether results were adjusted for total energy intake (TEI)) impacted the size or direction of the association. Finally, a dose-response analysis was planned, but not conducted due to limited evidence.

The outcomes for the quantitative synthesis were growth, body composition, and risk of obesity. The Committee planned to conduct meta-analyses on the following relationships:

- Intake of SSB at baseline and
  ○ growth (weight, weight-for-age; BMI-for-age, weight-for-length/stature; body circumferences (arm, neck, thigh); failure-to-thrive) at follow-up or change over time
  ○ body composition (skinfold thickness; fat mass; fat-free, lean mass; waist circumference, waist-to-hip ratio) at follow-up or change over time
  ○ risk of obesity (BMI; overweight and obesity; underweight; normal weight) at follow-up or change over time
- Change in intake of SSB and
  ○ growth (weight, weight-for-age; BMI-for-age, weight-for-length/stature; body circumferences (arm, neck, thigh); failure-to-thrive) at follow-up or change over time
  ○ body composition (skinfold thickness; fat mass; fat-free, lean mass; waist circumference, waist-to-hip ratio) at follow-up or change over time
  ○ risk of obesity (BMI; overweight and obesity; underweight; normal weight) at follow-up or change over time

#### Data preparation

Studies were combined statistically if they were sufficiently homogenous in study design, intervention/exposure, comparator, and effect size measure. NESR analysts selected the effect size, categorical comparisons, and/or measurement units that allowed the largest number of effects to be included in the analysis, as well as the most fully adjusted results. To maximize the data available for inclusion in the meta-analysis, NESR analysts converted results to a common effect size based on each outcome (Table A 5, Table A 14). Based on the available data, NESR analysts also transformed measurement units for both the exposure and the outcome (if needed) to analyze results on the same scale. NESR analysts did not combine outcomes measured at a single time point with outcomes measuring change over time (e.g., BMI z-score and change in BMI z-score), nor exposures that were reported continuously with results reported categorically (e.g., 8 oz/day and any intake versus no intake), as the results were not similarly scaled.

For cohort studies reporting continuous exposure data, results were scaled to represent the number of 12-oz servings/day for adults, and 8-oz servings/day for younger life stages. If studies did not specify a serving size, NESR analysts assumed the standard serving size of 12-oz servings/day and 8-oz servings/day for younger life stages. For cohort studies reporting categorical exposure data, analysts selected the most common comparison(s) across studies (e.g., ≥1 serving SSB/d versus never/rarely) to be included in the analysis. Comparisons that were not sufficiently similar were not included. If reported details were insufficient to permit transformation, NESR analysts contacted study authors to obtain usable data. If data transformations and/or contacting authors was unsuccessful, studies were excluded from the meta-analysis.

Where possible, data that were not adjusted for TEI were used because TEI mediates the relationship between SSB intake and growth, body composition, and risk of obesity.

Data were prepared using the software R (version 4.4.1).^*^

* R Core Team (2024). R: A language and environment for statistical computing. R Foundation for Statistical Computing, Vienna, Austria. URL https://www.R-project.org/.

#### Meta-analyses

For each relationship of interest, the main analysis included all effect sizes reported for that relationship. Studies were examined separately by study design (trials, cohort studies). For trials, the effect sizes were reported as mean differences or standardized mean differences. Regression coefficients (i.e., beta values), transformed to equivalent units, were used as the effect size for continuous outcomes in cohort studies because they were more commonly reported than mean differences. Odds ratios were reported for categorical outcomes. In all cases, the average effect size and 95% confidence interval (CI) were calculated using random-effects models with the restricted maximum-likelihood (REML) estimator.^†^ Statistical significance was set at a two-sided alpha of 0.05. When multiple acceptable measures of the intervention/exposure and/or the outcome were reported within a study, data were analyzed using multi-level meta-analysis to account for the multiplicity and dependence.

† Langan, D, Higgins, JP, Jackson, D, Bowden, J, Veroniki, AA, Kontopantelis, E, . A comparison of heterogeneity variance estimators in simulated random-effects meta-analyses. Research synthesis methods 2019; 10(1): 83–98. doi: 10.1002/jrsm.1316 30067315

All meta-analyses were conducted using the metafor package^‡^ (version 4.4-0) in the R software environment (version 4.4.1).

‡ Viechtbauer W. Conducting Meta-Analyses in R with the metafor Package. Journal of Statistical Software 2010; 36(3): 1–48. doi: 10.18637/jss.v036.i03

Planned meta-regression analyses (e.g., by dose-response, funding source, reasons for risk of bias) were not conducted if data were not available, or if the main and subgroup analyses showed consistent results with little heterogeneity.

#### Assessment of heterogeneity

NESR analysts developed forest plots by study design, type of intervention/exposure, and type of outcome. Heterogeneity was assessed visually by inspecting the forest plots for overlap of CI across the individual effect sizes. Additionally, the following measures of statistical heterogeneity were reported: estimates of the between-studies variance of effects (either τ^2^ for univariate analyses or σ^2^, the sum of hierarchical between-studies variance and between-effects variance for studies that report several effects), I^2^ (95% CI), and the 95% prediction interval (PI). NESR analysts then completed planned subgroup analyses and reported appropriate tests of between-groups differences. Sensitivity and study-by-study influence analyses were conducted as needed.

#### Assessment of non-reporting bias

When at least 10 unique studies or data points were included in an analysis and the included studies/data points varied in precision/sample size, non-reporting bias was evaluated with a visual assessment of asymmetry in a contour-enhanced funnel plot, a statistical test of funnel plot asymmetry (i.e., Egger’s Test), and an exploration of alternative causes of funnel plot asymmetry (e.g., heterogeneity). The trim-and-fill method was also used to indicate whether non-reporting bias was likely by estimating whether potentially missing studies would be statistically non-significant or would not support the hypothesized direction of the relationship between the exposure and outcome. When these criteria were not met, publication bias was addressed qualitatively without a funnel plot.

## Develop conclusion statements and grade the evidence

After the Committee synthesized the body of evidence, they drafted conclusion statements. A conclusion statement is one or more summary statements carefully constructed to answer the systematic review question. Each conclusion statement reflects the evidence reviewed, as outlined in the analytic framework (e.g., PICO elements) and synthesis plan, and does not take evidence from other sources into consideration. Conclusion statements do not draw implications and should not be interpreted as dietary guidance. The Committee reviewed, discussed, and revised the conclusion statements until they reached agreement on wording that accurately reflected the body of evidence.

The Committee then graded the strength of the evidence underlying each conclusion statement. They did this using NESR’s predefined criteria, based on 5 grading elements: consistency, precision, risk of bias, directness and generalizability of the evidence. Study design and publication bias were also considered.^*^

- [underlined: Consistency]: Consistency considers the degree of similarity in the direction and magnitude of effect across the body of evidence. This element also considers whether differences across the results can be explained by variations in study designs and methods.
- [underlined: Precision]: Precision considers the degree of certainty around an effect estimate for a given outcome. This element considers measures of variability, such as the width and range of confidence intervals, the number of studies, and sample sizes, within and across studies.
- [underlined: Risk of bias]: Risk of bias considers the likelihood that systematic errors resulting from the design and conduct of the studies could have impacted the accuracy of the reported results across the body of evidence.
- [underlined: Directness]: Directness considers the extent to which studies are designed to directly examine the relationship among the interventions/exposures, comparators, and outcome(s) of primary interest in the systematic review question.
- [underlined: Generalizability]: Generalizability considers whether the study participants, interventions and/or exposures, comparators, and outcomes examined in the body of evidence are applicable to the U.S. population of interest for the review.

* Spill MK, English LK, Raghavan R, . Perspective: USDA Nutrition Evidence Systematic Review Methodology: Grading the Strength of Evidence in Nutrition- and Public Health-Related Systematic Reviews. Adv Nutr. 2022 Aug 1;13(4):982–991. doi: 10.1093/advances/nmab147 34918032

The Committee assigned a grade to each conclusion statement (i.e., strong, moderate, limited, or grade not assignable). The grade communicates the strength of the evidence supporting a specific conclusion statement to decision makers and stakeholders. A conclusion statement can receive a grade of Strong, Moderate, or

Limited, and if insufficient or no evidence is available to answer a systematic review question, then no grade is assigned (i.e., Grade Not Assignable) (Table 4). The overall grade is not based on a predefined formula for scoring or tallying ratings of each element. Rather, each overall grade reflects the expert group’s thorough consideration of all of the grading elements, as they each relate to the specific nuances of the body of evidence under review.

Table 4 Definitions of NESR grades

Grade | Definition
Strong | The conclusion statement is based on a strong body of evidence as assessed by consistency, precision, risk of bias, directness, and generalizability. The level of certainty in the conclusion is strong, such that if new evidence emerges, modifications to the conclusion are unlikely to be required.
Moderate | The conclusion statement is based on a moderate body of evidence as assessed by consistency, precision, risk of bias, directness, and generalizability. The level of certainty in the conclusion is moderate, such that if new evidence emerges, modifications to the conclusion may be required.
Limited | The conclusion statement is based on a limited body of evidence as assessed by consistency, precision, risk of bias, directness, and generalizability. The level of certainty in the conclusion is limited, such that if new evidence emerges, modifications to the conclusion are likely to be required.
Grade Not Assignable | A conclusion statement cannot be drawn due to either a lack of evidence, or evidence that has severe limitations related to consistency, precision, risk of bias, directness, and generalizability.

## Recommend future research

The Committee identified and documented research gaps and methodological limitations throughout the systematic review process. These gaps and limitations will be used to develop research recommendations that describe the research, data, and methodological advances that are needed to strengthen the body of evidence on a particular topic. Rationales for the necessity of additional or stronger research are also provided with the research recommendations.

## Peer review

This systematic review underwent external peer review in a process coordinated by staff from the National Institutes of Health (NIH). NIH staff identified potential peer reviewers through outreach to a variety of professional organizations to select academic reviewers from U.S. colleges and universities across the country with a doctorate degree, including MDs, and expertise specific to the questions being reviewed. All peer reviewers were external to the Dietary Guidelines process, and therefore, current Committee members or Federal staff who supported the Committee or the development of the Dietary Guidelines were not eligible to serve as peer reviewers.

The peer review process was anonymous and confidential in that the peer reviewers were not identified to the Committee members or NESR staff, and in turn, the reviewers were asked not to share or discuss the review with anyone. Peer reviewers were made aware that per USDA, Food and Nutrition Service (FNS) agency policy, all peer reviewer comments would be summarized and made public, but comments would not be attributed to a specific reviewer.

Peer review occurred after draft conclusion statements were discussed by the full Committee at its third, fourth, fifth, and sixth public meetings. NIH staff assigned and distributed the reviews to at least 2 peer reviewers based on area of expertise. Following peer review, the Committee reviewed and discussed comments and made revisions to the systematic review, as needed, based on the discussion.

## Health equity considerations

The Committee was charged by HHS and USDA to review all scientific questions with a health equity lens to ensure that the next edition of the Dietary Guidelines is relevant to people with diverse racial, ethnic, socioeconomic, and cultural backgrounds. The Committee made a number of health equity considerations throughout the NESR systematic review process. The Committee’s Scientific Report^*^ includes a more detailed discussion of their approach to applying a health equity lens to their review of evidence, but examples include consideration of key confounders relevant to health equity and assessment of generalizability of the evidence.

* 2025 Dietary Guidelines Advisory Committee. 2024. Scientific Report of the 2025 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Health and Human Services and Secretary of Agriculture. U.S. Department of Health and Human Services. 10.52570/DGAC2025