# Plain language summary

### What is the question?

The question is: What is the relationship between sugar-sweetened beverage consumption and growth, body composition, and risk of obesity? The populations of interest for this question include infants and young children up to age 24 months, children, adolescents, adults, older adults, and individuals during pregnancy and postpartum.

### Why was this question asked?

This systematic review with meta-analysis was conducted by the 2025 Dietary Guidelines Advisory Committee as part of the process to develop the Dietary Guidelines for Americans, 2025-2030.

### How was this question answered?

The Committee conducted a systematic review with meta-analysis to answer this question with support from the USDA Nutrition Evidence Systematic Review team. This review updated an existing review that was conducted by the 2020 Dietary Guidelines Advisory Committee.

### What is the answer to the question?

- Sugar-sweetened beverage consumption by infants, children, and adolescents is associated with unfavorable growth patterns and body composition, and higher risk of obesity in childhood up to early adulthood. This conclusion statement is based on evidence graded as moderate.
- Sugar-sweetened beverage consumption by adults and older adults is associated with unfavorable body composition. This conclusion statement is based on evidence graded as moderate.
- Sugar-sweetened beverage consumption by adults and older adults is associated with higher risk of obesity. This conclusion statement is based on evidence graded as moderate.
- A conclusion statement cannot be drawn about the relationship between sugar-sweetened beverage consumption during pregnancy and adequacy of gestational weight gain because there is not enough evidence available, and there are substantial concerns with consistency, precision, risk of bias, directness, and generalizability in the available body of evidence.
- A conclusion statement cannot be drawn about the relationship between sugar-sweetened beverage consumption during postpartum and postpartum weight change because there is not enough evidence available.

### How up-to-date is this systematic review?

Conclusion statements from this review are based on articles published between January 2000 and May 2023.