# Acknowledgments

The Committee members were involved in: establishing all aspects of the protocol, which presented the plan for how they would examine the scientific evidence, including the inclusion and exclusion criteria; reviewing all studies that met the criteria they set; deliberating on the body of evidence for each question; and writing and grading the conclusion statements. The NESR team, with assistance from Federal staff from HHS and USDA (Jean Altman, MS; Kara Beckman, PhD; Dana DeSilva, PhD, RD; Kevin Kuczynski, MS, RD; TusaRebecca Pannucci, PhD, MPH, RD; Julia Quam, MSPH, RND; Elizabeth Rahavi, RD) and Project Leadership (Eve Stoody, PhD; Janet de Jesus, MS, RD), supported the Committee by facilitating, executing, and documenting the work necessary to ensure the reviews were completed in accordance with NESR methodology. Contractor support was also provided by Panum Telecom, LLC, a wholly owned subsidiary of Aretum (Emily Madan, PhD; Verena McClain, MSc; Sara Pritschet, MS, RD).

The Committee and NESR staff thank staff from the National Institutes of Health (NIH) (https://www.nichd.nih.gov/) for coordinating the peer review of this systematic review, and the peer reviewers for their time and expertise.