# Appendix 6 Meta-analysis supplementary materials

## SSB-Children

Table A 14 Data transformations and assumptions for meta-analyses in children^*^ * Abbreviations: β: regression coefficient; BMI: body mass index; CI: confidence interval; d: day; fl oz: fluid ounces; kcal: kilocalorie; L: liter; ln: natural log; MD: mean difference; mo: month; NR: not reported; OB: obesity; OR: odds ratio; OWO: overweight/obesity; oz: ounce; Q#: quartile; SE: standard error; SSB: sugar-sweetened beverage; svg: serving; T#: tertile; TEI: total energy intake; vs: versus; wk: week; x: times; y: year; Z: z-value

Reference Observation | Extracted Data | Transformations and Assumptions | Transformed Effect Estimate
Alviso-Orellana, 2018^2^ ≤1x/2wk | 4y change in BMI for ≤1x/2 wk SSB vs. never; β (95% CI); −0.08 (−0.39, 0.23) | Converted 95% CI to SE. | β (SE); −0.08 (0.16)
Alviso-Orellana, 2018^2^ 2–6x/wk | 4y change in BMI for 2–6x/wk SSB vs. never; β (95% CI); 0.14 (−0.15, 0.43) | Converted 95% CI to SE. | β (SE); 0.14 (0.15)
Alviso-Orellana, 2018^2^ 1x/d | 4y change in BMI for 1x/d SSB vs. never; β (95% CI) 0.74; (0.15, 1.33) | Converted 95% CI to SE. | β (SE); 0.74 (0.30)
Ambrosini, 2013^4^; Females; T2 vs. T1 | 3y change in BMI percentile for moved into >.0.5–1.3 svg/d SSB vs. stayed at 0–0.5 svg/d; β (95% CI); 0.4 (−1.3, 2.1) | Change in BMI percentile was converted to change in BMI based on BMI at baseline.; Converted 95% CI to SE. | β (SE); 0.08 (0.18)
Ambrosini, 2013^4^; Females; T3 vs. T1 | 3y change in BMI percentile for moved into >1.3 svg/d SSB vs. stayed at 0–0.5 svg/d; β (95% CI); 3.6 (1.5, 5.8) | Change in BMI percentile was converted to change in BMI based on BMI at baseline.; Converted 95% CI to SE. | β (SE); 0.78 (0.24)
Ambrosini, 2013^4^; Males; T2 vs. T1 | 3y change in BMI percentile for moved into >0.5–1.3 svg/d SSB vs. stayed at 0–0.5 svg/d; β (95% CI); 0.3 (−1.6, 2.3) | Change in BMI percentile was converted to change in BMI based on BMI at baseline.; Converted 95% CI to SE. | β (SE); 0.06 (0.21)
Ambrosini, 2013^4^; Males; T3 vs. T1 | 3y change in BMI percentile for moved into >1.3 svg/d SSB vs. stayed at 0–0.5 svg/d; β (95% CI); 0.8 (−1.3, 2.9) | Change in BMI percentile was converted to change in BMI based on BMI at baseline.; Converted 95% CI to SE. | β (SE); 0.17 (0.23)
Berkey, 2004^7^; Females; TEI unadjusted | 1y change in BMI per 12 oz/d; β (SE); 0.026 (0.015) | Coefficients were converted to 8 oz svg/d by multiplying estimates by 0.667. | β (SE); 0.02 (0.01)
Berkey, 2004^7^; Females; TEI adjusted | 1y change in BMI per 12 oz/d; β (SE); 0.023 (0.016) | Coefficients were converted to 8 oz svg/d by multiplying estimates by 0.667. | β (SE); 0.02 (0.01)
Berkey, 2004^7^; Males; TEI unadjusted | 1y change in BMI per 12 oz/d; β (SE); 0.040 (0.016) | Coefficients were converted to 8 oz svg/d by multiplying estimates by 0.667. | β (SE); 0.03 (0.01)
Berkey, 2004^7^; Males; TEI adjusted | 1y change in BMI per 12 oz/d; β (SE); 0.024 (0.018) | Coefficients were converted to 8 oz svg/d by multiplying estimates by 0.667. | β (SE); 0.02 (0.01)
Cantoral, 2016^10^; T2 vs. T1 | Odds of obesity based on BMIZ for 15,410–22,484 mL vs 1642–15,242 mL cumulative SSB consumption over 7–13 yr; OR (95% CI); 0.84 (0.32, 2.13) | Converted OR to ln(OR) and 95% CI to SE of ln(OR) for analysis. Back-transformed OR is presented in forest plot. | ln(OR) (SE); −0.17 (0.48)
Cantoral, 2016^10^; T3 vs. T1 | Odds of obesity based on BMIZ for 22,731–55,913 mL vs 1642–15,242 mL cumulative SSB consumption over 7–13 yr; OR (95% CI); 2.99 (1.27, 7) | Converted OR to ln(OR) and 95% CI to SE of ln(OR) for analysis. Back-transformed OR is presented in forest plot. | ln(OR) (SE); 1.10 (0.44)
Carlson, 2012^11^; BMIZ | BMIZ per 8 oz svg/d SSB; β (95% CI); 0.11 (−0.03, 0.25) | Converted 95% CI to SE | β (SE); 0.11 (0.07)
Carlson, 2012^11^; Body Fat % | Body fat percentage per 8 oz svg/d SSB; β (95% CI); 1.40 (0.09, 2.72) | Converted 95% CI to SE | β (SE); 1.40 (0.67)
Chen, 2019^13^ | 0.5y change in BMIZ per decrease in SSB; β (SE); −0.08 (0.03) | Change in BMIZ was converted to change in BMI using the LMS method. LMS values at 184.5 months were used and the average of Males and Females were calculated for the β and SE.; Serving size NR, assumed to be 8 oz. Coefficient was multiplied by −1 because results were reported per decrease in SSB. | β (SE); 0.23 (0.09)
De Coen, 2014^14^; 18 mo follow-up | Odds of overweight for 65 mL/d vs. ≤65 mL/d SSB; OR (95% CI) 1.45; (0.85, 2.48) | Converted OR to ln(OR) and 95% CI to SE of ln(OR) for analysis. Back-transformed OR is presented in forest plot. | ln(OR) (SE); 0.37 (0.27)
De Coen, 2014^14^; 30 mo follow-up | Odds of overweight for 65 mL/d vs. ≤65 mL/d SSB; OR (95% CI); 1.36 (0.77, 2.40) | Converted OR to ln(OR) and 95% CI to SE of ln(OR) for analysis. Back-transformed OR is presented in forest plot. | ln(OR) (SE); 0.31 (0.29)
de Ruyter, 2012^15^ | 1.5y change in BMIZ for sugar-free beverage intervention vs. sugary beverage control; MD (95% CI); −0.13 (−0.21, 0.05) | Converted 95% CI to SE; Change in BMIZ was converted to change in BMI using the LMS method. LMS values at 116.5 months were used and the average of Males and Females were calculated for the β and SE. | MD (SE); −0.13 (0.04)
Dubois, 2007^19^; Regular consumers vs. none | Odds of overweight for regular SSB consumers vs. nonconsumers; OR (95% CI); 2.16 (1.00, 4.70) | Converted OR to ln(OR) and 95% CI to SE of ln(OR) for analysis. Back-transformed OR is presented in forest plot. | ln(OR) (SE); 0.77 (0.39)
Dubois, 2007^19^; Others vs. none | Odds of overweight for “other” SSB consumers vs. nonconsumers; OR (95% CI); 1.15 (0.73, 1.82) | Converted OR to ln(OR) and 95% CI to SE of ln(OR) for analysis. Back-transformed OR is presented in forest plot. | ln(OR) (SE); 0.14 (0.23)
Ebbeling, 2006^23^; BMI T1 at baseline | 0.5y change in BMI for noncaloric beverage intervention vs. control; Information provided by authors | Information provided by authors | MD (SE); 0.48 (0.34)
Ebbeling, 2006^23^; BMI T2 at baseline | 0.5y change in BMI for noncaloric beverage intervention vs. control; Information provided by authors | Information provided by authors | MD (SE); −0.05 (0.34)
Ebbeling, 2006^23^; BMI T3 at baseline | 0.5y change in BMI for noncaloric beverage intervention vs. control; Information provided by authors | Information provided by authors | MD (SE); −0.75 (0.34)
Ebbeling, 2012^22^ | 1y change in BMI for multicomponent noncaloric beverage intervention vs. control; MD (SD): −0.57 (0.28) | The standard deviation was converted to a standard error. | MD (SE); −0.57 (0.02)
Enes, 2013^24^ | 1y change in BMIZ per change in sweetened fruit juice consumption; β (95% CI); 0.053 (0.004, 0.102) | Converted 95% CI to SE.; Change in BMIZ was converted to change in BMI using the LMS method. LMS values at 153.5 months were used and the average of Males and Females were calculated for the β and SE.; Serving size NR, assumed to be 8 oz. | β (SE); 0.14 (0.07)
English, 2022^25^; Increase in SSB intake; 1–<2 c/d more | 2y change in BMI for 1–<2 c/d more SSB; β (95% CI); 0.47 (−0.27, 1.22) | Converted 95% CI to SE | β (SE); 0.47 (0.38)
English, 2022^25^; Increase in SSB intake; ≥2 c/d more | 2y change in BMI for ≥2 c/d more SSB; β (95% CI); 0.42 (−0.39, 1.22) | Converted 95% CI to SE | β (SE); 0.42 (0.41)
English, 2022^25^; Decrease in SSB intake; ≥2 c/d less | 2y change in BMI for ≥2 c/d less SSB; β (95% CI); 0.14 (−0.47, 0.76) | Converted 95% CI to SE | β (SE); 0.14 (0.31)
English, 2022^25^; Decrease in SSB intake; 1–<2 c/d less | 2y change in BMI for 1–<2 c/d less SSB; β (95% CI); 0.17 (−0.40, 0.74) | Converted 95% CI to SE | β (SE); 0.17 (0.29)
English, 2022^25^; Decrease in SSB intake; <1 c/d less | 2y change in BMI for <1 c/d less SSB; β (95% CI); 0.29 (−0.28, 0.85) | Converted 95% CI to SE | β (SE); 0.29 (0.29)
Faith, 2006^26^; Any weight status at baseline | 6-mo change in BMIZ per 0.75 cups/d SSB; β (SE); 0.005 (0.002) | Change in BMIZ was converted to change in BMI using the LMS method. LMS values at 30.5 months were used and the average of Males and Females were calculated for the β and SE.; Coefficients were converted to 8 oz svg/d by multiplying estimates by 1.33. | β (SE); 0.01 (0.00)
Faith, 2006^26^; Weight Status ≥85th percentile at baseline | 6-mo change in BMIZ per 0.75 cups/d SSB; β (SE); 0.009 (0.003) | Change in BMIZ was converted to change in BMI using the LMS method. LMS values at 30.5 months were used and the average of Males and Females were calculated for the β and SE.; Coefficients were converted to 8 oz svg/d by multiplying estimates by 1.33. | β (SE); 0.02 (0.01)
Faith, 2006^26^; Weight Status <85th percentile at baseline | 6-mo change in BMIZ per 0.75 cups/d SSB; β (SE); 0.003 (0.002) | Change in BMIZ was converted to change in BMI using the LMS method. LMS values at 30.5 months were used and the average of Males and Females were calculated for the β and SE.; Coefficients were converted to 8 oz svg/d by multiplying estimates by 1.33. | β (SE); 0.01 (0.00)
Field, 2014^27^; Change in soda intake Females | 2.5y change in BMI per 2–3 yr change in 12 oz svg/d regular soda; β (95% CI); 0.12 (−0.05, 0.29) | Converted 95% CI to SE.; Coefficients were converted to 8 oz svg/d by multiplying estimates by 0.667. | β (SE); 0.08 (0.06)
Field, 2014^27^; Change in soda intake Males | 2.5y change in BMI per 2–3 yr change in 12 oz svg/d regular soda; β (95% CI); 0.14 (−0.02, 0.3) | Converted 95% CI to SE.; Coefficients were converted to 8 oz svg/d by multiplying estimates by 0.667. | β (SE); 0.09 (0.06)
Field, 2014^27^; Soda intake at baseline Females | 2.5y change in BMI per 12 oz svg/d regular soda; β (95% CI); 0.02 (−0.14, 0.19) | Converted 95% CI to SE.; Coefficients were converted to 8 oz svg/d by multiplying estimates by 0.667. | β (SE); 0.01 (0.06)
Field, 2014^27^; Soda intake at baseline Males | 2.5y change in BMI per 12 oz svg/d regular soda; β (95% CI); 0.09 (−0.06, 0.24) | Converted 95% CI to SE.; Coefficients were converted to 8 oz svg/d by multiplying estimates by 0.667. | β (SE); 0.06 (0.05)
Field, 2014^27^; Sports drink intake at baseline Females | 2.5y change in BMI per 12 oz svg/d sports drinks; β (95% CI); 0.29 (0.03, 0.54) | Converted 95% CI to SE.; Coefficients were converted to 8 oz svg/d by multiplying estimates by 0.667. | β (SE); 0.19 (0.09)
Field, 2014^27^; Sports drink intake at baseline Males | 2.5y change in BMI per 12 oz svg/d sports drinks; β (95% CI); 0.33 (0.09, 0.58) | Converted 95% CI to SE.; Coefficients were converted to 8 oz svg/d by multiplying estimates by 0.667. | β (SE); 0.22 (0.08)
Fiorito, 2009^28^; OWO; 7y; 1–<2 svg/d | 2y odds of overweight for 1–<2 svg/d SSB vs. <1 svg/d; n; <1 svg/d, with overweight: 14; <1 svg/d, without overweight: 79; 1–<2 svg/d, with overweight: 6; 1–<2 svg/d, without overweight: 45 | Calculated ln(OR) and SE of ln(OR) based on count data obtained from author communication. Back-transformed OR is presented in forest plot. | ln(OR) (SE); −0.29 (0.52)
Fiorito, 2009^28^; OWO; 7y; ≥2 svg/d | 2y odds of overweight for ≥2 svg/d SSB vs. <1 svg/d; n; <1 svg/d, with overweight: 14; <1 svg/d, without overweight: 79; ≥2 svg/d, with overweight:12; ≥2 svg/d, without overweight: 14 | Calculated ln(OR) and SE of ln(OR) based on count data obtained from author communication. Back-transformed OR is presented in forest plot. | ln(OR) (SE); 1.57 (0.49)
Fiorito, 2009^28^; OWO; 15y; 1–<2 svg/d | 10y odds of overweight for 1–<2 svg/d SSB vs. <1 svg/d; n; <1 svg/d, with overweight: 17; <1 svg/d, without overweight: 76; 1–<2 svg/d, with overweight: 9; 1–<2 svg/d, without overweight: 42 | Calculated ln(OR) and SE of ln(OR) based on count data obtained from author communication. Back-transformed OR is presented in forest plot. | ln(OR) (SE); −0.01 (0.46)
Fiorito, 2009^28^; OWO; 15y; ≥2 svg/d | 10y odds of overweight for ≥2 svg/d SSB vs. <1 svg/d; n; <1 svg/d, with overweight: 17; <1 svg/d, without overweight: 76; ≥2 svg/d, with overweight:8; ≥2 svg/d, without overweight: 18 | Calculated ln(OR) and SE of ln(OR) based on count data obtained from author communication. Back-transformed OR is presented in forest plot. | ln(OR) (SE); 0.73 (0.50)
Garden, 2011^30^ | 6.5y BMI for some vs. less sweetened drinks and juice consumption; β (95% CI); 0.04 (−0.17, 0.25) | Converted 95% CI to SE.; BMI was converted to BMIZ using the LMS method. LMS values at 96.5 months were used and the average of Males and Females were calculated for the β and SE. | β (SE); 0.04 (0.04)
Goff, 2019^32^ | 10y BMI for every day/most days SSB consumption vs. never; β (95% CI); 0.03 (−0.89, 0.84) | Converted 95% CI to SE.; BMI was converted to BMIZ using the LMS method. LMS values at 144.5 months were used and the average of Males and Females were calculated for the β and SE. | β (SE); 0.03 (0.44)
Gopinath, 2013^34^ | 5y change in BMI for ≥1 SSB/d vs. Never/rarely (<1/wk); β (SE); 1.24 (0.48) | Serving size NR, assumed to be 8 oz. | β (SE); 1.24 (0.48)
Guerrero, 2016^35^; All participants | 2y BMI for any soda vs. none; β (SE); 0.14 (0.04) | BMI was converted to BMIZ using the LMS method. LMS values at 60.5 months were used and the average of Males and Females were calculated for the β and SE. | β (SE); 0.08 (0.02)
Guerrero, 2016^35^; White participants | 2y BMI for any soda vs. none; β (SE); 0.09 (0.05) | BMI was converted to BMIZ using the LMS method. LMS values at 60.5 months were used and the average of Males and Females were calculated for the β and SE. | β (SE); 0.20 (0.16)
Guerrero, 2016^35^; Black participants | 2y BMI for any soda vs. none; β (SE); 0.29 (0.11) | BMI was converted to BMIZ using the LMS method. LMS values at 60.5 months were used and the average of Males and Females were calculated for the β and SE. | β (SE); 0.51 (0.41)
Guerrero, 2016^35^; Asian participants | 2y BMI for any soda vs. none; β (SE); 0.07 (0.10) | BMI was converted to BMIZ using the LMS method. LMS values at 60.5 months were used and the average of Males and Females were calculated for the β and SE. | β (SE); 0.04 (0.07)
Guerrero, 2016^35^; Hispanic-English participants | 2y BMI for any soda vs. none; β (SE); 0.03 (0.14) | BMI was converted to BMIZ using the LMS method. LMS values at 60.5 months were used and the average of Males and Females were calculated for the β and SE. | β (SE); 0.48 (0.54)
Guerrero, 2016^35^; Hispanic-Spanish participants | 2y BMI for any soda vs. none; β (SE); 0.23 (0.12) | BMI was converted to BMIZ using the LMS method. LMS values at 60.5 months were used and the average of Males and Females were calculated for the β and SE. | β (SE); 0.59 (0.52)
Haines, 2007^36^; Any weight status at baseline Females | 5y odds of overweight per svg/d SSB; OR (95% CI); 1.34 (1.00, 1.81) | Converted OR to ln(OR) and 95% CI to SE of ln(OR) for analysis. Back-transformed OR is presented in forest plot.; Serving size NR, 8 oz was assumed. | ln(OR) (SE); 0.29 (0.15)
Haines, 2007^36^; Any weight status at baseline Males | 5y odds of overweight per svg/d SSB; OR (95% CI); 0.82 (0.58, 1.17) | Converted OR to ln(OR) and 95% CI to SE of ln(OR) for analysis. Back-transformed OR is presented in forest plot.; Serving size NR, 8 oz was assumed. | ln(OR) (SE); −0.20 (0.18)
Haines, 2007^36^; Without OWO at baseline Females | 5y odds of incident overweight per svg/d SSB; OR (95% CI); 1.41 (0.95, 2.12) | Converted OR to ln(OR) and 95% CI to SE of ln(OR) for analysis. Back-transformed OR is presented in forest plot.; Serving size NR, 8 oz was assumed. | ln(OR) (SE); 0.34 (0.20)
Haines, 2007^36^; Without OWO at baseline Males | 5y odds of incident overweight per svg/d SSB; OR (95% CI); 0.63 (0.37, 1.07) | Converted OR to ln(OR) and 95% CI to SE of ln(OR) for analysis. Back-transformed OR is presented in forest plot.; Serving size NR, 8 oz was assumed. | ln(OR) (SE); −0.46 (0.27)
He, 2022^38^ | 0.5y odds of obesity per times/wk SSB; OR; 1.004, p=0.441 | Converted OR to ln(OR) for analysis. Estimated SE of ln(OR) from p-value using absolute value of ln(OR)/Z. Back-transformed OR is presented in forest plot.; Serving size NR, assumed 8 oz svg/time. Coefficients were converted to 8 oz svg/d by multiplying estimates by 7. | ln(OR) (SE); 0.03 (0.19)
Hur, 2016^40^; BMIZ | 4y BMIZ per g/d SSB; β (SE); −0.02 (0.02) | Coefficients were converted from g/d to 8 oz svg/d by multiplying by 22.2. (USDA FDC notes 1 fl oz svg includes 2.78 g sugar) | β (SE); −0.44 (0.44)
Hur, 2016^40^; Body Fat % Females | 4y body fat percentage per g/d SSB; β (SE); 0.12 (0.23) | Coefficients were converted to 8 oz servings by multiplying estimates by 22.2 (USDA FDC notes 1 fl oz svg includes 2.78 g sugar). | β (SE); 2.66 (5.10)
Hur, 2016^40^; Body Fat % Males | 4y body fat percentage per g/d SSB; β (SE); −0.08 (0.35) | Coefficients were converted to 8 oz servings by multiplying estimates by 22.2 (USDA FDC notes 1 fl oz svg includes 2.78 g sugar). | β (SE); −1.78 (7.77)
Jensen, 2013a^42^; BAEW; Increase in SSB intake Low SEP | 2y change in BMIZ for 100 mL/d increase in SSB vs. no change; β (95% CI); −0.05 (−0.18, 0.09) | Converted 95% CI to SE.; Change in BMIZ was converted to change in BMI using the LMS method. LMS values at 117.5 months were used and the average of Males and Females were calculated for the β and SE. | β (SE); −0.10 (0.14)
Jensen, 2013a^42^; BAEW; Increase in SSB intake High SEP | 2y change in BMIZ for 100 mL/d increase in SSB vs. no change; β (95% CI); 0.13 (0.00, 0.25) | Converted 95% CI to SE.; Change in BMIZ was converted to change in BMI using the LMS method. LMS values at 123.5 months were used and the average of Males and Females were calculated for the β and SE. | β (SE); 0.29 (0.14)
Jensen, 2013a^42^; BAEW; Decrease in SSB intake Low SEP | 2y change in BMIZ for 100 mL/d decrease in SSB vs. no change; β (95% CI); −0.01 (−0.11, 0.08) | Converted 95% CI to SE.; Change in BMIZ was converted to change in BMI using the LMS method. LMS values at 117.5 months were used and the average of Males and Females were calculated for the β and SE. | β (SE); −0.03 (0.10)
Jensen, 2013a^42^; BAEW; Decrease in SSB intake High SEP | 2y change in BMIZ for 100 mL/d decrease in SSB vs. no change; β (95% CI); 0.10 (−0.12, 0.31) | Converted 95% CI to SE.; Change in BMIZ was converted to change in BMI using the LMS method. LMS values at 123.5 months were used and the average of Males and Females were calculated for the β and SE. | β (SE); 0.22 (0.25)
Jensen, 2013a^42^; BAEW; SSB intake at baseline | 2y change in BMIZ per 100 mL/d SSB; β (95% CI); 0.01 (−0.00, 0.01) | Converted 95% CI to SE.; Change in BMIZ was converted to change in BMI using the LMS method. LMS values at 120.5 months were used and the average of Males and Females were calculated for the β and SE.; Coefficients were converted to 8 oz svg/d by multiplying estimates by 2.367. | β (SE); 0.03 (0.02)
Jensen, 2013b^43^; Change in SSB intake; CoSCIS | 3y change in BMI per 100 mL/d change in SSB; β (95% CI); 0.04 (−0.04, 0.11) | Converted 95% CI to SE.; Coefficients were converted to 8 oz svg/d by multiplying estimates by 2.367. | β (SE); 0.08 (0.06)
Jensen, 2013b^43^; CoSCIS; SSB intake at baseline Sweet drinks | 3.5y change in BMI per 100 mL/d all sweet drinks; β (95% CI); −0.05 (−0.12, 0.02) | Converted 95% CI to SE.; Coefficients were converted to 8 oz svg/d by multiplying estimates by 2.367. | β (SE); −0.12 (0.09)
Jensen, 2013b^43^; CoSCIS; SSB intake at baseline Soft drinks | 3.5y change in BMI per 100 mL/d soft drinks; β (95% CI); −0.04 (−0.22, 0.15) | Converted 95% CI to SE.; Coefficients were converted to 8 oz svg/d by multiplying estimates by 2.367. | β (SE); −0.08 (0.22)
Jensen, 2013c^42^; IYM; Increase in SSB intake | 2y change in BMIZ for 100 mL/d increase in SSB vs. no change; β (95% CI); −0.03 (−0.12, 0.07) | Converted 95% CI to SE.; Change in BMIZ was converted to change in BMI using the LMS method. LMS values at 202.5 months were used and the average of Males and Females were calculated for the β and SE. | β (SE); −0.08 (0.15)
Jensen, 2013c^42^; IYM; Decrease in SSB intake | 2y change in BMIZ for 100 mL/d decrease in SSB vs. no change; β (95% CI); −0.08 (−0.19, 0.03) | Converted 95% CI to SE.; Change in BMIZ was converted to change in BMI using the LMS method. LMS values at 202.5 months were used and the average of Males and Females were calculated for the β and SE. | β (SE); −0.23 (0.17)
Jensen, 2013c^42^; IYM; SSB intake at baseline | 2y change in BMIZ per 100 mL/d SSB; β (95% CI); 0.004 (−0.00, 0.01) | Converted 95% CI to SE.; Change in BMIZ was converted to change in BMI using the LMS method. LMS values at 199.5 months were used and the average of Males and Females were calculated for the β and SE.; Coefficients were converted to 8 oz svg/d by multiplying estimates by 2.367. | β (SE); 0.03 (0.02)
Johnson, 2012^44^ | 2.5y change in BMIZ per 250 mL/d SSB; β (95% CI); 0.015 (0.00, 0.03) | Converted 95% CI to SE.; Change in BMIZ was converted to change in BMI using the LMS method. LMS values at 126.5 months were used and the average of Males and Females were calculated for the β and SE.; Coefficients were converted to 8 oz svg/d by multiplying estimates by 0.947. | β (SE); 0.03 (0.02)
Katan, 2016^46^; “Overweight” at baseline | 1.5y change in BMIZ for sugar-free beverage intervention vs. sugar-containing beverage control; MD (95% CI); −0.23 (−0.36, −0.10) | Converted 95% CI to SE.; Change in BMIZ was converted to change in BMI using the LMS method. LMS values at 116.5 months were used and the average of Males and Females were calculated for the β and SE. | MD (SE); −0.23 (0.07)
Katan, 2016^46^; “Lean” at baseline | 1.5y change in BMIZ for sugar-free beverage intervention vs. sugar-containing beverage control; MD (95% CI); −0.10 (−0.19, −0.02) | Converted 95% CI to SE.; Change in BMIZ was converted to change in BMI using the LMS method. LMS values at 116.5 months were used and the average of Males and Females were calculated for the β and SE. | MD (SE); −0.10 (0.04)
Kuhl, 2014^48^ | 0.5y change in BMIZ per change in fl oz/d SSB; β (SE); 0.014 (0.01) | Change in BMIZ was converted to change in BMI using the LMS method. LMS values at 62.5 months were used and the average of Males and Females were calculated for the β and SE.; Coefficients were converted to 8 oz svg/d by multiplying values by 8. | β (SE); 0.14 (0.13)
Kunaratnam, 2020^49^ | 1.5y odds of overweight/obesity per 250 mL/d SSB; OR (95% CI); 0.55 (0.21, 1.47) | Converted OR to ln(OR) and 95% CI to SE of ln(OR) for analysis. Back-transformed OR is presented in forest plot.; Coefficients were converted to 8 oz svg/d by multiplying values by 0.95. | ln(OR) (SE); −0.57 (0.47)
Larson, 2018^50^; Females | 17y odds of maintaining a healthy weight per per 1 SD unit greater intake SSB; OR (95% CI); 0.73 (0.58, 0.91) | Converted OR for maintaining healthy weight to ln(OR) for developing overweight using the following calculation: ln(1/OR). Converted 95% CI to SE of ln(OR) for analysis. Back-transformed OR is presented in forest plot.; Serving size NR, assumed to be 8 oz. Value of SD unit (0.8750 svg/d) obtained via author communication. Coefficients were converted to svg/d by multiplying values by 1.14. | ln(OR) (SE); 0.36 (0.13)
Larson, 2018^50^; Males | 17y odds of maintaining a healthy weight per per 1 SD unit greater intake SSB; OR (95% CI); 0.80 (0.64, 1.00) | Converted OR for maintaining healthy weight to ln(OR) for developing overweight using the following calculation: ln(1/OR). Converted 95% CI to SE of ln(OR) for analysis. Back-transformed OR is presented in forest plot.; Serving size NR, assumed to be 8 oz. Value of SD unit (0.9336 svg/d) obtained via author communication. Coefficients were converted to svg/d by multiplying values by 1.07. | ln(OR) (SE) 0.23901409; (0.12194596)
Laska, 2012^51^; Females; TEI unadjusted | 2y change in BMI per svg/d change in SSB; β (SE); −0.09 (0.16) | Serving size NR, assumed to be 8 oz. | β (SE); −0.09 (0.16)
Laska, 2012^51^; Females; TEI adjusted | 2y change in BMI per svg/d change in SSB; β (SE); −0.05 (0.17) | Serving size NR, assumed to be 8 oz. | β (SE); −0.05 (0.17)
Laska, 2012^51^; Males; TEI unadjusted | 2y change in BMI per svg/d change in SSB; β (SE); 0.25 (0.10) | Serving size NR, assumed to be 8 oz. | β (SE); 0.25 (0.10)
Laska, 2012^51^; Males; TEI adjusted | 2y change in BMI per svg/d change in SSB; β (SE); 0.27 (0.10) | Serving size NR, assumed to be 8 oz. | β (SE); 0.27 (0.10)
Laurson, 2008^52^; Change in SSB intake; Females; Any weight status at baseline | 1.5y change in BMI per svg/wk change in SSB; β (SE); 0.09 (0.03) | Serving size NR, assumed to be 8 oz/svg. Coefficients were converted to svg/d by multiplying values by 7. | β (SE); 0.60 (0.19)
Laurson, 2008^52^; Change in SSB intake; Females; Weight status <85th percentile at baseline | 1.5y change in BMI per svg/wk change in SSB; β (SE); 0.004 (0.028) | Serving size NR, assumed to be 8 oz/svg. Coefficients were converted to svg/d by multiplying values by 7. | β (SE); 0.03 (0.20)
Laurson, 2008^52^; Change in SSB intake; Males; Any weight status at baseline | 1.5y change in BMI per svg/wk change in SSB; β (SE); −0.04 (0.02) | Serving size NR, assumed to be 8 oz/svg. Coefficients were converted to svg/d by multiplying values by 7. | β (SE); −0.26 (0.13)
Laurson, 2008^52^; Change in SSB intake; Males; Weight status <85th percentile at baseline | 1.5y change in BMI per svg/wk change in SSB; β (SE); −0.05 (0.02) | Serving size NR, assumed to be 8 oz/svg. Coefficients were converted to svg/d by multiplying values by 7. | β (SE); −0.36 (0.16)
Laurson, 2008^52^; SSB intake at baseline; Males; Any weight status at baseline | 1.5y change in BMI per svg/wk SSB; β (SE); 0.11 (0.02) | Serving size NR, assumed to be 8 oz/svg. Coefficients were converted to svg/d by multiplying values by 7. | β (SE); 0.80 (0.15)
Laurson, 2008^52^; SSB intake at baseline; Males; Weight status <85th percentile at baseline | 1.5y change in BMI per svg/wk SSB; β (SE); 0.13 (0.02) | Serving size NR, assumed to be 8 oz/svg. Coefficients were converted to svg/d by multiplying values by 7. | β (SE); 0.79 (0.15)
Laurson, 2008^52^; SSB intake at baseline; Females; Any weight status at baseline | 1.5y change in BMI per svg/wk SSB; β (SE); 0.02 (0.02) | Serving size NR, assumed to be 8 oz/svg. Coefficients were converted to svg/d by multiplying values by 7. | β (SE); 0.15 (0.15)
Laurson, 2008^52^; SSB intake at baseline; Females; Weight status <85th percentile at baseline | 1.5y change in BMI per svg/wk SSB; β (SE); 0.004 (0.02) | Serving size NR, assumed to be 8 oz/svg. Coefficients were converted to svg/d by multiplying values by 7. | β (SE); 0.03 (0.14)
Lee, 2015^53^; Females; TEI unadjusted | 1y change in BMIZ per 1 tsp change in liquid added sugar intake; β (95% CI); 0.002 (0.001, 0.003) | Converted 95% CI to SE.; Change in BMIZ was converted to change in BMI using the LMS method. LMS values at 144.5 months for Females were used.; Coefficients were converted to 8 oz svg/d by multiplying estimates by 5.7 (USDA FDC notes 1 fl oz svg includes 2.78 g sugar). | β (SE); 0.03 (0.01)
Lee, 2015^53^; Females; TEI adjusted | 1y change in BMIZ per 1 tsp change in liquid added sugar intake; β (95% CI); 0.001 (0.000, 0.002) | Converted 95% CI to SE.; Change in BMIZ was converted to change in BMI using the LMS method. LMS values at 144.5 months for Females were used.; Coefficients were converted to 8 oz svg/d by multiplying estimates by 5.7 (USDA FDC notes 1 fl oz svg includes 2.78 g sugar). | β (SE); 0.01 (0.01)
Leermakers, 2015^54^; BMIZ; 2 y; Males; 8 svg/wk | 1y BMIZ for medium (median: 8.0 svg/wk) vs. low (median: 3.1 svg/wk) SSB consumption; β (95% CI); −0.02 (−0.15, 0.11) | Converted 95% CI to SE. | β (SE); −0.02 (0.07)
Leermakers, 2015^54^; BMIZ; 2 y; Males; 15 svg/wk | 1y BMIZ for high (median: 14.9 svg/wk) vs. low (median: 3.1 svg/wk) SSB consumption; β (95% CI); −0.01 (−0.15, 0.12) | Converted 95% CI to SE. | β (SE); −0.01 (0.07)
Leermakers, 2015^54^; BMIZ; 6 y; Males; 8 svg/wk | 5y BMIZ for medium (median: 8.0 svg/wk) vs. low (median: 3.1 svg/wk) SSB consumption; β (95% CI); −0.02 (−0.14, 0.10) | Converted 95% CI to SE. | β (SE); −0.02 (0.06)
Leermakers, 2015^54^; BMIZ; 6 y; Males; 15 svg/wk | 5y BMIZ for high (median: 14.9 svg/wk) vs. low (median: 3.1 svg/wk) SSB consumption; β (95% CI); 0.05 (−0.08, 0.18) | Converted 95% CI to SE. | β (SE); 0.05 (0.07)
Leermakers, 2015^54^; BMIZ; 2 y; Females; 8 svg/wk | 1y BMIZ for medium (median: 8.0 svg/wk) vs. low (median: 3.1 svg/wk) SSB consumption; β (95% CI); 0.03 (−0.12, 0.16) | Converted 95% CI to SE. | β (SE); 0.03 (0.07)
Leermakers, 2015^54^; BMIZ; 2 y; Females; 15 svg/wk | 1y BMIZ for high (median: 14.9 svg/wk) vs. low (median: 3.1 svg/wk) SSB consumption; β (95% CI); 0.15 (0.01, 0.30) | Converted 95% CI to SE. | β (SE); 0.15 (0.07)
Leermakers, 2015^54^; BMIZ; 6 y; Females; 8 svg/wk | 5y BMIZ for medium (median: 8.0 svg/wk) vs. low (median: 3.1 svg/wk) SSB consumption; β (95% CI); 0.01 (−0.11, 0.13) | Converted 95% CI to SE. | β (SE); 0.01 (0.06)
Leermakers, 2015^54^; BMIZ; 6 y; Females; 15 svg/wk | 5y BMIZ for high (median: 14.9 svg/wk) vs. low (median: 3.1 svg/wk) SSB consumption; β (95% CI); 0.11 (0.00, 0.23) | Converted 95% CI to SE. | β (SE); 0.11 (0.06)
Leermakers, 2015^54^; OWO; Males; 2y; 8 svg/wk | 1y odds of overweight/obesity for medium (median: 8.0 svg/wk) vs. low (median: 3.1 svg/wk) SSB consumption; OR (95% CI); 0.86 (0.43, 1.74) | Converted OR to ln(OR) and 95% CI to SE of ln(OR) for analysis. Back-transformed OR is presented in forest plot. | ln(OR) (SE); −0.15 (0.36)
Leermakers, 2015^54^; OWO; Males; 2y; 15 svg/wk | 1y odds of overweight/obesity for high (median: 14.9 svg/wk) vs. low (median: 3.1 svg/wk) SSB consumption; OR (95% CI); 1.09 (0.57, 2.11) | Converted OR to ln(OR) and 95% CI to SE of ln(OR) for analysis. Back-transformed OR is presented in forest plot. | ln(OR) (SE); 0.09 (0.33)
Leermakers, 2015^54^; OWO; Males; 6y; 8 svg/wk | 5y odds of overweight/obesity for medium (median: 8.0 svg/wk) vs. low (median: 3.1 svg/wk) SSB consumption; OR (95% CI); 1.03 (0.57, 1.88) | Converted OR to ln(OR) and 95% CI to SE of ln(OR) for analysis. Back-transformed OR is presented in forest plot. | ln(OR) (SE); 0.03 (0.30)
Leermakers, 2015^54^; OWO; Males; 6y; 15 svg/wk | 5y odds of overweight/obesity for high (median: 14.9 svg/wk) vs. low (median: 3.1 svg/wk) SSB consumption; OR (95% CI); 0.90 (0.44, 1.85) | Converted OR to ln(OR) and 95% CI to SE of ln(OR) for analysis. Back-transformed OR is presented in forest plot. | ln(OR) (SE); −0.11 (0.37)
Leermakers, 2015^54^; OWO; Females; 2y; 8 svg/wk | 1y odds of overweight/obesity for medium (median: 8.0 svg/wk) vs. low (median: 3.1 svg/wk) SSB consumption; OR (95% CI); 1.12 (0.61, 2.03) | Converted OR to ln(OR) and 95% CI to SE of ln(OR) for analysis. Back-transformed OR is presented in forest plot. | ln(OR) (SE); 0.11 (0.31)
Leermakers, 2015^54^; OWO; Females; 2y; 15 svg/wk | 1y odds of overweight/obesity for high (median: 14.9 svg/wk) vs. low (median: 3.1 svg/wk) SSB consumption; OR (95% CI); 1.40 (0.76, 2.56) | Converted OR to ln(OR) and 95% CI to SE of ln(OR) for analysis. Back-transformed OR is presented in forest plot. | ln(OR) (SE); 0.34 (0.31)
Leermakers, 2015^54^; OWO; Females; 6y; 8 svg/wk | 5y odds of overweight/obesity for medium (median: 8.0 svg/wk) vs. low (median: 3.1 svg/wk) SSB consumption; OR (95% CI); 1.09 (0.67, 1.78) | Converted OR to ln(OR) and 95% CI to SE of ln(OR) for analysis. Back-transformed OR is presented in forest plot. | ln(OR) (SE); 0.09 (0.25)
Leermakers, 2015^54^; OWO; Females; 6y; 15 svg/wk | 5y odds of overweight/obesity for high (median: 14.9 svg/wk) vs. low (median: 3.1 svg/wk) SSB consumption; OR (95% CI); 1.27 (0.78, 2.06) | Converted OR to ln(OR) and 95% CI to SE of ln(OR) for analysis. Back-transformed OR is presented in forest plot. | ln(OR) (SE); 0.24 (0.25)
Lewis, 2020^56^; 6mo-<2y; Several/wk | 1y change in BMIZ for several SSB/wk vs. ≤1x/wk; β (95% CI); −0.23 (−0.58, 0.13) | Converted 95% CI to SE.; Change in BMIZ was converted to change in BMI using the LMS method. LMS values at 27.5 months were used and the average of Males and Females were calculated for the β and SE. | β (SE); −0.29 (0.24)
Lewis, 2020^56^; 6mo-<2y; 1x/d | 1y change in BMIZ for 1x/d SSB vs. ≤1x/wk; β (95% CI); −0.23 (−0.51, 0.05) | Converted 95% CI to SE.; Change in BMIZ was converted to change in BMI using the LMS method. LMS values at 27.5 months were used and the average of Males and Females were calculated for the β and SE. | β (SE); −0.29 (0.19)
Lewis, 2020^56^; 6mo-<2y; 2x/d | 1y change in BMIZ for 2x/d SSB vs. ≤1x/wk; β (95% CI); −0.001 (−0.34, 0.34) | Converted 95% CI to SE.; Change in BMIZ was converted to change in BMI using the LMS method. LMS values at 27.5 months were used and the average of Males and Females were calculated for the β and SE. | β (SE); −0.00 (0.23)
Lewis, 2020^56^; 6mo-<2y; ≥3x/d | 1y change in BMIZ for ≥3x/d SSB vs. ≤1x/wk; β (95% CI); −0.03 (−0.4, 0.33) | Converted 95% CI to SE.; Change in BMIZ was converted to change in BMI using the LMS method. LMS values at 27.5 months were used and the average of Males and Females were calculated for the β and SE. | β (SE); −0.04 (0.25)
Lewis, 2020^56^; 2–5y; Several/wk | 1y change in BMIZ for several SSB/wk vs. ≤1x/wk; β (95% CI); 0.08 (−0.27, 0.43) | Converted 95% CI to SE.; Change in BMIZ was converted to change in BMI using the LMS method. LMS values at 54.5 months were used and the average of Males and Females were calculated for the β and SE. | β (SE); −0.10 (0.22)
Lewis, 2020^56^; 2–5y; 1x/d | 1y change in BMIZ for 1x/d SSB vs. ≤1x/wk; β (95% CI); 0.09 (−0.20, 0.38) | Converted 95% CI to SE.; Change in BMIZ was converted to change in BMI using the LMS method. LMS values at 54.5 months were used and the average of Males and Females were calculated for the β and SE. | β (SE); 0.11 (0.18)
Lewis, 2020^56^; 2–5y; 2x/d | 1y change in BMIZ for 2x/d SSB vs. ≤1x/wk; β (95% CI); 0.30 (−0.002, 0.60) | Converted 95% CI to SE.; Change in BMIZ was converted to change in BMI using the LMS method. LMS values at 54.5 months were used and the average of Males and Females were calculated for the β and SE. | β (SE); 0.37 (0.19)
Lewis, 2020^56^; 2–5y; ≥3x/d | 1y change in BMIZ for ≥3x/d SSB vs. ≤1x/wk; β (95% CI); 0.35 (0.04, 0.65) | Converted 95% CI to SE.; Change in BMIZ was converted to change in BMI using the LMS method. LMS values at 54.5 months were used and the average of Males and Females were calculated for the β and SE. | β (SE); 0.44 (0.19)
Lewis, 2020^56^; 6–11y; Several/wk | 1y change in BMIZ for several SSB/wk vs. ≤1x/wk; β (95% CI); 0.11 (−0.04, 0.26) | Converted 95% CI to SE.; Change in BMIZ was converted to change in BMI using the LMS method. LMS values at 114.5 months were used and the average of Males and Females were calculated for the β and SE. | β (SE); 0.23 (0.16)
Lewis, 2020^56^; 6–11y; 1x/d | 1y change in BMIZ for 1x/d SSB vs. ≤1x/wk; β (95% CI); 0.16 (0.02, 0.29) | Converted 95% CI to SE.; Change in BMIZ was converted to change in BMI using the LMS method. LMS values at 114.5 months were used and the average of Males and Females were calculated for the β and SE. | β (SE); 0.34 (0.14)
Lewis, 2020^56^; 6–11y; 2x/d | 1y change in BMIZ for 2x/d SSB vs. ≤1x/wk; β (95% CI); 0.18 (0.04, 0.32) | Converted 95% CI to SE.; Change in BMIZ was converted to change in BMI using the LMS method. LMS values at 114.5 months were used and the average of Males and Females were calculated for the β and SE. | β (SE); 0.38 (0.15)
Lewis, 2020^56^; 6–11y; ≥3x/d | 1y change in BMIZ for ≥3x/d SSB vs. ≤1x/wk; β (95% CI); 0.18 (0.04, 0.32) | Converted 95% CI to SE.; Change in BMIZ was converted to change in BMI using the LMS method. LMS values at 114.5 months were used and the average of Males and Females were calculated for the β and SE. | β (SE); 0.38 (0.15)
Lewis, 2020^56^; 12–17y; Several/wk | 1y change in BMIZ for several SSB/wk vs. ≤1x/wk; β (95% CI); 0.09 (−0.03, 0.21) | Converted 95% CI to SE.; Change in BMIZ was converted to change in BMI using the LMS method. LMS values at 186.5 months were used and the average of Males and Females were calculated for the β and SE. | β (SE); 0.26 (0.18)
Lewis, 2020^56^; 12–17y; 1x/d | 1y change in BMIZ for 1x/d SSB vs. ≤1x/wk; β (95% CI); 0.21 (0.10, 0.31) | Converted 95% CI to SE.; Change in BMIZ was converted to change in BMI using the LMS method. LMS values at 186.5 months were used and the average of Males and Females were calculated for the β and SE. | β (SE); 0.63 (0.16)
Lewis, 2020^56^; 12–17y; 2x/d | 1y change in BMIZ for 2x/d SSB vs. ≤1x/wk; β (95% CI); 0.17 (0.05, 0.28) | Converted 95% CI to SE.; Change in BMIZ was converted to change in BMI using the LMS method. LMS values at 186.5 months were used and the average of Males and Females were calculated for the β and SE. | β (SE); 0.51 (0.17)
Lewis, 2020^56^; 12–17y; ≥3x/d | 1y change in BMIZ for ≥3x/d SSB vs. ≤1x/wk; β (95% CI); 0.15 (0.04, 0.26) | Converted 95% CI to SE.; Change in BMIZ was converted to change in BMI using the LMS method. LMS values at 186.5 months were used and the average of Males and Females were calculated for the β and SE. | β (SE); 0.45 (0.16)
Libuda, 2008^58^; BMIZ; Females | 1y BMIZ per MJ/d*time regular soft drinks; β (SE); 0.005 (0.03) | Coefficients were converted from MJ/d (~240 kcal) to 8 oz svg/d by multiplying estimates by 1.40 (USDA FDC notes that soda contains ~42 kcal/fl oz) | β (SE); 0.01 (0.05)
Libuda, 2008^58^; BMIZ; Males | 1y BMIZ per MJ/d*time regular soft drinks; β (SE); 0.04 (0.03) | Coefficients were converted from MJ/d (~240 kcal) to 8 oz svg/d by multiplying estimates by 1.40 (USDA FDC notes that soda contains ~42 kcal/fl oz) | β (SE); 0.05 (0.04)
Libuda, 2008^58^; Body Fat %; Males | 1y body fat percentage per MJ/d*time regular soft drinks; β (SE); −0.033 (0.33) | Coefficients were converted from MJ/d (~240 kcal) to 8 oz svg/d by multiplying estimates by 1.40 (USDA FDC notes that soda contains ~42 kcal/fl oz) | β (SE); −0.05 (0.46)
Libuda, 2008^58^; Body Fat %; Females | 1y body fat percentage per MJ/d*time regular soft drinks; β (SE); 0.006 (0.37) | Coefficients were converted from MJ/d (~240 kcal) to 8 oz svg/d by multiplying estimates by 1.40 (USDA FDC notes that soda contains ~42 kcal/fl oz) | β (SE); 0.01 (0.52)
Lim, 2009^59^; BMI; Decrease vs. no change in SSB intake | 2y change in BMIZ for decrease in SSB intake vs. no change; β (SE); −0.13 (0.23) | Change in BMIZ was converted to change in BMI using the LMS method. LMS values at 72.5 months were used and the average of Males and Females were calculated for the β and SE. | β (SE); 0.17 (0.33)
Lim, 2009^59^; BMI; Decrease vs. increase in SSB intake | 2y change in BMIZ for decrease in SSB intake vs. increase; β (SE); 0.01 (0.19) | Change in BMIZ was converted to change in BMI using the LMS method. LMS values at 72.5 months were used and the average of Males and Females were calculated for the β and SE. | β (SE); −0.01 (0.27)
Lim, 2009^59^; OWO | 2y odds of overweight per oz/d SSB; OR (95% CI); 1.04 (1.01, 1.07) | Converted OR to ln(OR) and 95% CI to SE of ln(OR) for analysis. Back-transformed OR is presented in forest plot.; Coefficients were converted to 8 oz svg/d by multiplying estimates by 8. | ln(OR) (SE); 0.31 (0.12)
Lipsky, 2015^60^; Change in SSB intake | 1y change in BMI per change in sugar-sweetened soda consumption; β (SE); −0.15 (0.12) | Serving size NR, assumed to be 8 oz. | β (SE); −0.15 (0.12)
Lipsky, 2015^60^; SSB intake at baseline | 1y change in BMI per sugar-sweetened soda consumption; β (SE); 0.01 (0.04) | Serving size NR, assumed to be 8 oz. | β (SE); 0.01 (0.04)
Ludwig, 2001^61^; Change in SSB intake; Change in BMI | 1.6y change in BMI per change in SSB consumption; β (95% CI); 0.24 (0.10, 0.39) | Converted 95% CI to SE.; Serving size NR, assumed to be 8 oz. | β (SE); 0.24 (0.07)
Ludwig, 2001^61^; OWO | 1.6y odds of obesity per SSB consumption; OR (95% CI); 1.48 (0.63, 3.47) | Converted OR to ln(OR) and 95% CI to SE of ln(OR) for analysis. Back-transformed OR is presented in forest plot.; Serving size NR, assumed to be 8 oz. | ln(OR) (SE); 0.39 (0.44)
Ludwig, 2001^61^; SSB intake at baseline; Change in BMI | 1.6y change in BMI per SSB consumption; β (95% CI); 0.18 (0.09, 0.27) | Converted 95% CI to SE.; Serving size NR, assumed to be 8 oz. | β (SE); 0.18 (0.05)
Macintyre, 2018^62^; 1–6 x/wk | 3y odds of overweight/obesity for 1–6 x/wk SSB vs; <1x/wk; OR (95% CI); 0.94 (0.68, 1.30) | Converted OR to ln(OR) and 95% CI to SE of ln(OR) for analysis. Back-transformed OR is presented in forest plot. | ln(OR) (SE); −0.06 (0.17)
Macintyre, 2018^62^; ≥1 x/wk | 3y odds of overweight/obesity for ≥1–6 x/wk SSB vs <1x/wk; OR (95% CI); 1.18 (0.92, 1.52) | Converted OR to ln(OR) and 95% CI to SE of ln(OR) for analysis. Back-transformed OR is presented in forest plot. | ln(OR) (SE); 0.17 (0.13)
Mahoney, 2018^63^; 12 mo; Any/wk | 1.5y BMIZ for any SSB consumption vs. none; β (95% CI); 0.07 (−0.08, 0.23) | Converted 95% CI to SE | β (SE); 0.07 (0.08)
Mahoney, 2018^63^; 18 mo; >7 svg/wk | 2y BMIZ for >7 svg/wk SSB vs. ≤7 svg/wk; β (95% CI); −0.01 (−0.18, 0.16) | Converted 95% CI to SE | β (SE); −0.01 (0.09)
Marshall, 2019^66^; All participants; SSB | BMIZ per 8 oz/d SSB; β (95% CI); 0.05 (0.02, 0.08) | Converted 95% CI to SE | β (SE); 0.05 (0.01)
Marshall, 2019^66^; ≤9 y; Fruit juice | BMIZ per 8 oz/d fruit juice; β (95% CI); −0.03 (−0.11, 0.06) | Converted 95% CI to SE | β (SE); −0.03 (0.04)
Marshall, 2019^66^; ≤9 y; SSB | BMIZ per 8 oz/d SSB; β (95% CI); 0.08 (−0.02, 0.18) | Converted 95% CI to SE | β (SE); 0.08 (0.05)
Millar, 2014^67^ | 4y change in BMIZ per change in SSB consumption; β (95% CI); 0.015 (0.004, 0.025) | Converted 95% CI to SE.; Change in BMIZ was converted to change in BMI using the LMS method. LMS values at 105.5 months were used and the average of Males and Females were calculated for the β and SE.; Serving size NR, assumed to be 8 oz. | β (SE); 0.03 (0.01)
Mirmiran, 2015^68^; SSB; Q2 vs. Q1 | 3.6y odds of abdominal obesity for Q2 (median 32.0 mL/d) vs. Q1 (median 9.3 mL/d) SSB consumption; OR (95% CI); 1.58 (0.65, 3.86) | Converted OR to ln(OR) and 95% CI to SE of ln(OR) for analysis. Back-transformed OR is presented in forest plot. | ln(OR) (SE); 0.46 (0.45)
Mirmiran, 2015^68^; SSB; Q3 vs. Q1 | 3.6y odds of abdominal obesity for Q3 (median 58.6 mL/d) vs. Q1 (median 9.3 mL/d) SSB consumption; OR (95% CI); 1.70 (0.70, 4.09) | Converted OR to ln(OR) and 95% CI to SE of ln(OR) for analysis. Back-transformed OR is presented in forest plot. | ln(OR) (SE); 0.53 (0.45)
Mirmiran, 2015^68^; SSB; Q4 vs. Q1 | 3.6y odds of abdominal obesity for Q4 (median 142.2 mL/d) vs. Q1 (median 9.3 mL/d) SSB consumption; OR (95% CI); 2.97 (1.23, 7.19) | Converted OR to ln(OR) and 95% CI to SE of ln(OR) for analysis. Back-transformed OR is presented in forest plot. | ln(OR) (SE); 1.09 (0.45)
Mirmiran, 2015^68^; Sugar-sweetened carbonated soft drinks; Q2 vs. Q1 | 3.6y odds of abdominal obesity for Q2 (median 9.33 mL/d) vs. Q1 (median 1.12 mL/d) sugar-sweetened carbonated soft drinks consumption; OR (95% CI); 1.85 (0.76, 4.49) | Converted OR to ln(OR) and 95% CI to SE of ln(OR) for analysis. Back-transformed OR is presented in forest plot. | ln(OR) (SE); 0.62 (0.45)
Mirmiran, 2015^68^; Sugar-sweetened carbonated soft drinks; Q3 vs. Q1 | 3.6y odds of abdominal obesity for Q3 (median 33.06 mL/d) vs. Q1 (median 1.12 mL/d) sugar-sweetened carbonated soft drinks consumption; OR (95% CI); 2.23 (0.91, 5.43) | Converted OR to ln(OR) and 95% CI to SE of ln(OR) for analysis. Back-transformed OR is presented in forest plot. | ln(OR) (SE); 0.80 (0.46)
Mirmiran, 2015^68^; Sugar-sweetened carbonated soft drinks; Q4 vs. Q1 | 3.6y odds of abdominal obesity for Q4 (median 100.00 mL/d) vs. Q1 (median 1.12 mL/d) sugar-sweetened carbonated soft drinks consumption; OR (95% CI); 3.39 (1.08, 10.70) | Converted OR to ln(OR) and 95% CI to SE of ln(OR) for analysis. Back-transformed OR is presented in forest plot. | ln(OR) (SE); 1.22 (0.59)
Mirmiran, 2015^68^; Fruit juice drink; Q2 vs. Q1 | 3.6y odds of abdominal obesity for Q2 (median 8.29 mL/d) vs. Q1 (median 1.31 mL/d) fruit juice drink consumption; OR (95% CI); 1.53 (0.69, 3.78) | Converted OR to ln(OR) and 95% CI to SE of ln(OR) for analysis. Back-transformed OR is presented in forest plot. | ln(OR) (SE); 0.43 (0.43)
Mirmiran, 2015^68^; Fruit juice drink; Q3 vs. Q1 | 3.6y odds of abdominal obesity for Q3 (median 20.40 mL/d) vs. Q1 (median 1.31 mL/d) fruit juice drink consumption; OR (95% CI); 0.72 (0.29, 1.77) | Converted OR to ln(OR) and 95% CI to SE of ln(OR) for analysis. Back-transformed OR is presented in forest plot. | ln(OR) (SE); −0.33 (0.46)
Mirmiran, 2015^68^; Fruit juice drink; Q4 vs. Q1 | 3.6y odds of abdominal obesity for Q4 (median 67.14 mL/d) vs. Q1 (median 1.31 mL/d) fruit juice drink consumption; OR (95% CI); 1.15 (0.48, 2.77) | Converted OR to ln(OR) and 95% CI to SE of ln(OR) for analysis. Back-transformed OR is presented in forest plot. | ln(OR) (SE); 0.14 (0.45)
Muckelbauer, 2016^70^; SSB | 0.7y change in BMI per 200 mL glass change in SSB consumption; β (95% CI); 0.02 (0.00, 0.03) | Converted 95% CI to SE.; Coefficients were converted from to 8 oz servings by multiplying estimates by 1.183. | β (SE); 0.02 (0.01)
Muckelbauer, 2016^70^; Juice | 0.7y change in BMI per 200 mL glass change in juice consumption; β (95% CI); 0.01 (−0.01, 0.03) | Converted 95% CI to SE.; Coefficients were converted from to 8 oz servings by multiplying estimates by 1.183. | β (SE); 0.01 (0.01)
Muckelbauer, 2016^70^; Soft drinks | 0.7y change in BMI per 200 mL glass change in soft drink consumption; β (95% CI); 0.02 (0.00, 0.04) | Converted 95% CI to SE.; Coefficients were converted from to 8 oz servings by multiplying estimates by 1.183. | β (SE); 0.02 (0.01)
Newby, 2004^72^; Soda | 0.7y change in BMI per oz/d non-diet soda; β (SE); −0.01 (0.02) | Coefficients were converted from 1 oz to 8 oz servings by multiplying estimates by 8 | β (SE); −0.08 (0.16)
Newby, 2004^72^; Fruit drinks | 0.7y change in BMI per oz/d fruit drinks; β (SE); −0.01 (0.01) | Coefficients were converted from 1 oz to 8 oz servings by multiplying estimates by 8 | β (SE); −0.08 (0.08)
Nissinen, 2009^73^; BMI; Males | 21y BMI per 10 unit/mo change in sugar-sweetened soft drinks; β (SE); 0.01 (0.01) | Assumed 1 unit = 8 oz. Coefficients were converted to 8 oz servings by multiplying estimates by 3. | β (SE); 0.03 (0.03)
Nissinen, 2009^73^; BMI; Females | 21y BMI per 10 unit/mo change in sugar-sweetened soft drinks; β (SE); −0.16 (0.14) | Assumed 1 unit = 8 oz. Coefficients were converted to 8 oz servings by multiplying estimates by 3. | β (SE); −0.48 (0.42)
Nissinen, 2009^73^; OWO; Females | 21y odds of overweight per unit/mo greater intake of sugar-sweetened soft drinks; β (SE); −0.005 (0.007) | Serving size NR, assumed 8 oz svg/mo. Coefficients were converted to 8 oz svg/d by multiplying values by 30.4167.; Transformed to OR for presentation in forest plot. | ln(OR) (SE); −0.16 (0.21)
Nissinen, 2009^73^; OWO; Males | 21y odds of overweight per unit/mo greater intake of sugar-sweetened soft drinks; β (SE); −0.004 (0.007) | Serving size NR, assumed 8 oz svg/mo. Coefficients were converted to 8 oz svg/d by multiplying values by 30.4167.; Transformed to OR for presentation in forest plot. | ln(OR) (SE); −0.12 (0.22)
Pan, 2014^75^; <1 x/wk vs. none | 5y odds of obesity for <1 x/wk SSB vs. none; OR (95% CI); 1.64 (0.65, 4.14) | Converted OR to ln(OR) and 95% CI to SE of ln(OR) for analysis. Back-transformed OR is presented in forest plot. | ln(OR) (SE); 0.49 (0.47)
Pan, 2014^75^; 1–<3 x/wk vs. none | 5y odds of obesity for 1–<3 x/wk SSB vs. none; OR (95% CI); 1.51 (0.65, 3.48) | Converted OR to ln(OR) and 95% CI to SE of ln(OR) for analysis. Back-transformed OR is presented in forest plot. | ln(OR) (SE); 0.41 (0.43)
Pan, 2014^75^; ≥3 x/wk vs. none | 5y odds of obesity for ≥3 x/wk SSB vs. none; OR (95% CI); 2.00 (1.02, 3.9) | Converted OR to ln(OR) and 95% CI to SE of ln(OR) for analysis. Back-transformed OR is presented in forest plot. | ln(OR) (SE); 0.69 (0.34)
Pereyra-Gonzales, 2023^76^ | 2y change in BMIZ for any SSB consumption vs. no consumption; β (95% CI); −0.02 (−0.1, 0.06) | Converted 95% CI to SE.; Change in BMIZ was converted to change in BMI using the LMS method. LMS values at 49.5 months were used and the average of Males and Females were calculated for the β and SE. | β (SE); −0.02 (0.05)
Phillips, 2004^77^; Females; Q2 vs. Q1 | 10y BMIZ for 0.75–1.4% daily kcal vs. <0.74% daily kcal from sugar-sweetened soda; β; 0.089, p=0.03 | Estimated SE from p-value and β using SE=β/Z. | β (SE); 0.09 (0.04)
Phillips, 2004^77^; Females; Q3 vs. Q1 | 10y BMIZ for 1.5–3.1% daily kcal vs. <0.74% daily kcal from sugar-sweetened soda; β; 0.172, p=0.0009 | Estimated SE from p-value and β using SE=β/Z. | β (SE); 0.17 (0.05)
Phillips, 2004^77^; Females; Q4 vs. Q1 | 10y BMIZ for ≥3.2% daily kcal vs. <0.74% daily kcal from sugar-sweetened soda; β; 0.178, p=0.001 | Estimated SE from p-value and β using SE=β/Z. | β (SE); 0.18 (0.05)
Quah, 2019^78^; Continuous intake; 18 mo; TEI unadjusted | 1y BMIZ per 100 mL/d SSB; β (95% CI); 0.06 (−0.002, 0.12) | Converted 95% CI to SE. Coefficients were converted from 100 mL/d to 8 oz svg/d by multiplying estimates by 2.367. | β (SE); 0.14 (0.07)
Quah, 2019^78^; Continuous intake; 18 mo; TEI adjusted | 1y BMIZ per 100 mL/d SSB; β (95% CI); 0.05 (−0.01, 0.11) | Converted 95% CI to SE. Coefficients were converted from 100 mL/d to 8 oz svg/d by multiplying estimates by 2.367. | β (SE); 0.12 (0.07)
Quah, 2019^78^; Continuous intake; 5 y; TEI unadjusted | 4.5y BMIZ per 100 mL/d SSB; β (95% CI); 0.09 (0.03, 0.15) | Converted 95% CI to SE. Coefficients were converted from 100 mL/d to 8 oz svg/d by multiplying estimates by 2.367. | β (SE); 0.21 (0.07)
Quah, 2019^78^; Continuous intake; 5 y; TEI adjusted | 4.5y BMIZ per 100 mL/d SSB; β (95% CI); 0.09 (0.02, 0.16) | Converted 95% CI to SE. Coefficients were converted from 100 mL/d to 8 oz svg/d by multiplying estimates by 2.367. | β (SE); 0.21 (0.08)
Quah, 2019^78^; Categorical intake; 18 mo; T2 vs. T1 | 1y BMIZ for medium (median: 28 mL/d) vs. low (median: 2 mL/d) SSB consumption; β (95% CI); −0.05 (−0.29, 0.20) | Converted 95% CI to SE. | β (SE); −0.05 (0.12)
Quah, 2019^78^; Categorical intake; 18 mo; T3 vs. T1 | 1y BMIZ for high (median: 138 mL/d) vs. low (median: 2 mL/d) SSB consumption; β (95% CI); 0.08 (−0.17, 0.33) | Converted 95% CI to SE. | β (SE); 0.08 (0.13)
Quah, 2019^78^; Categorical intake; 5 y; T2 vs. T1 | 1y BMIZ for medium (median: 28 mL/d) vs. low (median: 2 mL/d) SSB consumption; β (95% CI); 0.17 (−0.05, 0.38) | Converted 95% CI to SE. | β (SE); 0.17 (0.11)
Quah, 2019^78^; Categorical intake; 5 y; T3 vs. T1 | 1y BMIZ for high (median: 138 mL/d) vs. low (median: 2 mL/d) SSB consumption; β (95% CI); 0.33 (0.11, 0.55) | Converted 95% CI to SE. | β (SE); 0.33 (0.11)
Quick, 2013^79^; Females | 10y odds of overweight/obesity per svg/d soda; OR (95% CI); 1.14 (0.95, 1.38) | Converted OR to ln(OR) and 95% CI to SE of ln(OR) for analysis. Back-transformed OR is presented in forest plot.; Serving size NR, assumed to be 8 oz. | ln(OR) (SE); 0.13 (0.10)
Quick, 2013^79^; Males | 10y odds of overweight/obesity per svg/d soda; OR (95% CI); 1.09 (0.91, 1.31) | Converted OR to ln(OR) and 95% CI to SE of ln(OR) for analysis. Back-transformed OR is presented in forest plot.; Serving size NR, assumed to be 8 oz. | ln(OR) (SE); 0.09 (0.09)
Seo, 2015^80^; Persistent OWO | 1.5y odds of persistent overweight/obesity vs. persistent non-overweight/obesity; OR (95% CI); 1.07 (1.03, 1.11) | Converted OR to ln(OR) and 95% CI to SE of ln(OR) for analysis. Back-transformed OR is presented in forest plot.; Serving size NR, assumed to be 8 oz. | ln(OR) (SE); 0.07 (0.02)
Seo, 2015^80^; Deteriorated weight status | 1.5y odds of deteriorated weight (normal/underweight to overweight/obesity, or overweight to obesity) vs. persistent non-overweight/obesity; OR (95% CI); 1.08 (1.01, 1.15) | Converted OR to ln(OR) and 95% CI to SE of ln(OR) for analysis. Back-transformed OR is presented in forest plot.; Serving size NR, assumed to be 8 oz. | ln(OR) (SE); 0.08 (0.03)
Shroff, 2014^82^; ≥1/d | 1y change in BMI for ≥1 soda/d vs. never; β (95% CI); 0.20 (0.04, 0.36) | Converted 95% CI to SE. | β (SE); 0.20 (0.08)
Shroff, 2014^82^; 2–6/wk | 1y change in BMI for 2–6 sodas/wk vs. never; β (95% CI); 0.12 (−0.01, 0.25) | Converted 95% CI to SE. | β (SE); 0.12 (0.07)
Shroff, 2014^82^; 1/mo to 1/wk | 1y change in BMI for 1/mo to 1/wk soda consumption vs. never; β (95% CI); 0.11 (0.00, 0.22) | Converted 95% CI to SE. | β (SE); 0.11 (0.06)
Shroff, 2014^82^; <1/mo | 1y change in BMI for <1 soda/mo vs. never; β (95% CI); 0.06 (−0.06, 0.19) | Converted 95% CI to SE. | β (SE); 0.06 (0.06)
Sichieri, 2013^83^ | 0.75y change in BMI per 250 mL/d soda; β (95% CI); 0.11 (0.03, 0.25) | Converted 95% CI to SE.; Coefficients were converted from to 8 oz svg/d by multiplying estimates by 0.947. | β (SE); 0.10 (0.05)
Sonneville, 2015^84^; 3.1 y; 1–7 oz/d | 2.1y BMIZ for 1–7 oz/d fruit juice intake vs. none; β (95% CI); 0.03 (−0.1, 0.15) | Converted 95% CI to SE. | β (SE); 0.03 (0.06)
Sonneville, 2015^84^; 3.1 y; 8–15 oz/d | 2.1y BMIZ for 8–15 oz/d fruit juice intake vs. none; β (95% CI); 0.17 (0.01, 0.33) | Converted 95% CI to SE. | β (SE); 0.17 (0.08)
Sonneville, 2015^84^; 3.1 y; >16 oz/d | 2.1y BMIZ for >16 oz/d fruit juice intake vs. none; β (95% CI); 0.30 (−0.01, 0.61) | Converted 95% CI to SE. | β (SE); 0.30 (0.16)
Sonneville, 2015^84^; 7.7 y; 1–7 oz/d | 6.7y BMIZ for 1–7 oz/d fruit juice intake vs. none; β (95% CI); 0.07 (−0.06, 0.21) | Converted 95% CI to SE. | β (SE); 0.07 (0.07)
Sonneville, 2015^84^; 7.7 y; 8–15 oz/d | 6.7y BMIZ for 8–15 oz/d fruit juice intake vs. none; β (95% CI); 0.23 (0.05, 0.40) | Converted 95% CI to SE. | β (SE); 0.23 (0.09)
Sonneville, 2015^84^; 7.7 y; >16 oz/d | 6.7y BMIZ for >16 oz/d fruit juice intake vs. none; β (95% CI); 0.27 (−0.05, 0.59) | Converted 95% CI to SE. | β (SE); 0.27 (0.16)
Stoof, 2013^85^; Body Fat %; Males | 27y body fat percentage per 220 mL/d SSB; β (95% CI); 1.10 (−0.02, 2.21) | Converted 95% CI to SE.; Coefficients were converted to 8 oz servings by multiplying estimates by 1.08. | β (SE); 1.19 (0.61)
Stoof, 2013^85^; Body Fat %; Females | 27y body fat percentage per 220 mL/d SSB; β (95% CI); −0.72 (−2.40, 0.97) | Converted 95% CI to SE.; Coefficients were converted to 8 oz servings by multiplying estimates by 1.08. | β (SE); −0.78 (0.93)
Stoof, 2013^85^; Change in BMI; Females | 27y change in BMI per 220 mL/d SSB; β (95% CI); 0.44 (−0.37, 1.24) | Converted 95% CI to SE.; Coefficients were converted to 8 oz servings by multiplying estimates by 1.08. | β (SE); 0.48 (0.44)
Stoof, 2013^85^; Change in BMI; Males | 27y change in BMI per 220 mL/d SSB; β (95% CI); 0.24 (−0.34, 0.81) | Converted 95% CI to SE.; Coefficients were converted to 8 oz servings by multiplying estimates by 1.08. | β (SE); 0.26 (0.32)
Striegel-Moore, 2006^86^; Females, Soda | 10y BMI per 100 g/d regular soda; β (SE); 0.011 (0.005) | BMI was converted to BMIZ using the LMS method. LMS values for Females at 120.5 months were used for the β and SE.; Coefficients were converted from 100 g to 8 oz servings by multiplying estimates by 2.48 (USDA FDC notes that juice averages 31 g/oz) | β (SE); 0.01 (0.00)
Striegel-Moore, 2006^86^; Females, Fruit drinks | 10y BMI per 100 g/d fruit drinks; β (SE); 0.009 (0.007) | BMI was converted to BMIZ using the LMS method. LMS values for Females at 120.5 months were used for the β and SE.; Coefficients were converted from 100 g to 8 oz servings by multiplying estimates by 2.48 (USDA FDC notes that juice averages 31 g/oz) | β (SE); 0.01 (0.01)
Thurber, 2017^88^; BMI | 1y BMI for <2 occasions/d SSB vs. ≥2 occasions/d; β (95% CI); −0.2 (−0.39, −0.01) | Converted 95% CI to SE.; Effect estimate was multiplied by −1 to reflect a higher vs. lower intake comparison.; BMI was converted to BMIZ using the LMS method. LMS values at 60.5 months were used and the average of Males and Females were calculated for the β and SE. | β (SE); 0.04 (0.72)
Thurber, 2017^88^; Change in BMI | 1y BMI for <2 occasions/d SSB vs. ≥2 occasions/d; β (95% CI); −0.05 (−0.14, 0.03) | Converted 95% CI to SE.; Effect estimate was multiplied by −1 to reflect a higher vs. lower intake comparison. | β (SE); 0.05 (0.04)
Traub, 2018^89^ | 1y odds of overweight for >1x/wk soft drink vs. ≤1x/wk; OR (95% CI); 1.29 (0.84, 1.96) | Converted OR to ln(OR) and 95% CI to SE of ln(OR) for analysis. Back-transformed OR is presented in forest plot. | ln(OR) (SE); 0.25 (0.22)
Trier, 2016^90^; Males; Low vs. Medium | 1.3y change in BMIZ for low vs. medium SSB consumption; β (95% CI); 0.027 (−0.039, 0.093) | Converted 95% CI to SE.; Effect estimate was multiplied by −1 to reflect a higher vs. lower intake comparison.; Change in BMIZ was converted to change in BMI using the LMS method. LMS values for Males at 153.5 months were used. | β (SE); −0.07 (0.09)
Trier, 2016^90^; Males; High vs. Medium | 1.3y change in BMIZ for high vs. medium SSB consumption; β (95% CI); 0.009 (−0.056, 0.074) | Converted 95% CI to SE.; Change in BMIZ was converted to change in BMI using the LMS method. LMS values for Males at 153.5 months were used. | β (SE); 0.02 (0.09)
Trier, 2016^90^; Females; Low vs. Medium | 1.3y change in BMIZ for low vs. medium SSB consumption; β (95% CI); 0.034 (−0.008, 0.075) | Converted 95% CI to SE.; Effect estimate was multiplied by −1 to reflect a higher vs. lower intake comparison.; Change in BMIZ was converted to change in BMI using the LMS method. LMS values for Females at 153.5 months were used. | β (SE); −0.09 (0.06)
Trier, 2016^90^; Females; High vs. Medium | 1.3y change in BMIZ for high vs. medium SSB consumption; β (95% CI); 0.012 (−0.033, 0.057) | Converted 95% CI to SE.; Change in BMIZ was converted to change in BMI using the LMS method. LMS values for Females at 153.5 months were used. | β (SE); 0.03 (0.18)
Vandyousefi, 2021^91^; OW (but not OB) | Odds of overweight for any SSB consumption vs. no SSB or 100% juice; OR (95% CI); 1.31 (0.69, 2.50) | Converted OR to ln(OR) and 95% CI to SE of ln(OR) for analysis. Back-transformed OR is presented in forest plot. | ln(OR) (SE); 0.27 (0.33)
Vandyousefi, 2021^91^; OB | Odds of obesity for any SSB consumption vs. no SSB or 100% juice; OR (95% CI); 3.22 (1.55, 6.67) | Converted OR to ln(OR) and 95% CI to SE of ln(OR) for analysis. Back-transformed OR is presented in forest plot. | ln(OR) (SE); 1.17 (0.37)
Vinke, 2020^94^; OWO; Q2 vs. Q1 | 5y odds of overweight/obesity for 2.7 SSB/d vs. 1.9/d; OR (95% CI); 2.30 (1.15, 4.57) | Converted OR to ln(OR) and 95% CI to SE of ln(OR) for analysis. Back-transformed OR is presented in forest plot. | ln(OR) (SE); 0.83 (0.35)
Vinke, 2020^94^; OWO; Q3 vs. Q1 | 5y odds of overweight/obesity for 3.6 SSB/d vs. 1.9/d; OR (95% CI); 2.13 (1.09, 4.17) | Converted OR to ln(OR) and 95% CI to SE of ln(OR) for analysis. Back-transformed OR is presented in forest plot. | ln(OR) (SE); 0.76 (0.34)
Vinke, 2020^94^; OWO; Q4 vs. Q1 | 5y odds of overweight/obesity for 4.9 SSB/d vs. 1.9/d; OR (95% CI); 3.12 (1.60, 6.07) | Converted OR to ln(OR) and 95% CI to SE of ln(OR) for analysis. Back-transformed OR is presented in forest plot. | ln(OR) (SE); 1.14 (0.34)
Vinke, 2020^94^; Change in BMI; Q2 vs. Q1 | 5y change in BMIZ for 2.7 SSB/d vs. 1.9/d; β (95% CI); 0.122 (0.014, 0.229) | Converted 95% CI to SE.; Change in BMIZ was converted to change in BMI using the LMS method. LMS values at 132.5 months were used and the average of Males and Females were calculated for the β and SE. | β (SE); 0.29 (0.13)
Vinke, 2020^94^; Change in BMI; Q3 vs. Q1 | 5y change in BMIZ for 3.6 SSB/d vs. 1.9/d; β (95% CI); 0.066 (−0.041, 0.174) | Converted 95% CI to SE.; Change in BMIZ was converted to change in BMI using the LMS method. LMS values at 132.5 months were used and the average of Males and Females were calculated for the β and SE. | β (SE); 0.16 (0.13)
Vinke, 2020^94^; Change in BMI; Q4 vs. Q1 | 5y change in BMIZ for 4.9 SSB/d vs. 1.9/d; β (95% CI); 0.160 (0.050, 0.271) | Converted 95% CI to SE.; Change in BMIZ was converted to change in BMI using the LMS method. LMS values at 132.5 months were used and the average of Males and Females were calculated for the β and SE. | β (SE); 0.39 (0.13)
Wang, 2022^95^; Change in BMIZ; Observational data Decreased SSB vs increased | 1y change in BMIZ for decreased SSB vs. increased; β (95% CI); −0.057 (−0.103, −0.012) | Converted 95% CI to SE.; Effect estimate was multiplied by −1 to reflect a higher vs. lower intake comparison.; Change in BMIZ was converted to change in BMI using the LMS method. LMS values at 124.5 months were used and the average of Males and Females were calculated for the β and SE. | β (SE); 0.13 (0.05)
Wang, 2022^95^; Change in BMIZ; Observational data No change in SSB vs. increased | 1y change in BMIZ for no change in SSB vs. increased; β (95% CI); −0.028 (−0.1, 0.045) | Converted 95% CI to SE.; Effect estimate was multiplied by −1 to reflect a higher vs. lower intake comparison.; Change in BMIZ was converted to change in BMI using the LMS method. LMS values at 124.5 months were used and the average of Males and Females were calculated for the β and SE. | β (SE); 0.06 (0.08)
Wang, 2022^95^; Change in BMI; RCT data | 1y change in BMI for multicomponent intervention targeting decrease in SSB consumption vs. control; MD (95% CI); −0.26 (−0.38, −0.12) | Converted 95% CI to SE. | MD (SE); −0.26 (0.07)
Welsh, 2005^96^; BMI <85% at baseline; 1–<2 drinks/d | 1y odds of overweight for 1–<2 sweet drinks/d vs. 0–<1 sweet drinks/d; OR (95% CI); 1.50 (0.90, 2.40) | Converted OR to ln(OR) and 95% CI to SE of ln(OR) for analysis. Back-transformed OR is presented in forest plot. | ln(OR) (SE); 0.41 (0.25)
Welsh, 2005^96^; BMI <85% at baseline; 2–<3 drinks/d | 1y odds of overweight for 2–<3 sweet drinks/d vs. 0–<1 sweet drinks/d; OR (95% CI); 1.40 (0.80, 2.30) | Converted OR to ln(OR) and 95% CI to SE of ln(OR) for analysis. Back-transformed OR is presented in forest plot. | ln(OR) (SE); 0.34 (0.27)
Welsh, 2005^96^; BMI <85% at baseline; ≥3 drinks/d | 1y odds of overweight for ≥3 sweet drinks/d vs. 0–<1 sweet drinks/d; OR (95% CI); 1.30 (0.80, 2.10) | Converted OR to ln(OR) and 95% CI to SE of ln(OR) for analysis. Back-transformed OR is presented in forest plot. | ln(OR) (SE); 0.26 (0.25)
Welsh, 2005^96^; BMI 85–<95% at baseline; 1–<2 drinks/d | 1y odds of overweight for 1–<2 sweet drinks/d vs. 0–<1 sweet drinks/d; OR (95% CI); 2.00 (1.30, 3.20) | Converted OR to ln(OR) and 95% CI to SE of ln(OR) for analysis. Back-transformed OR is presented in forest plot. | ln(OR) (SE); 0.69 (0.23)
Welsh, 2005^96^; BMI 85–<95% at baseline; 2–<3 drinks/d | 1y odds of overweight for 2–<3 sweet drinks/d vs. 0–<1 sweet drinks/d; OR (95% CI); 2.00 (1.20, 3.20) | Converted OR to ln(OR) and 95% CI to SE of ln(OR) for analysis. Back-transformed OR is presented in forest plot. | ln(OR) (SE); 0.69 (0.25)
Welsh, 2005^96^; BMI 85–<95% at baseline; ≥3 drinks/d | 1y odds of overweight for ≥3 sweet drinks/d vs. 0–<1 sweet drinks/d; OR (95% CI); 1.80 (1.10, 2.80) | Converted OR to ln(OR) and 95% CI to SE of ln(OR) for analysis. Back-transformed OR is presented in forest plot. | ln(OR) (SE); 0.59 (0.24)
Welsh, 2005^96^; BMI ≥95% at baseline; 1–<2 drinks/d | 1y odds of overweight for 1–<2 sweet drinks/d vs. 0–<1 sweet drinks/d; OR (95% CI); 2.10 (1.30, 3.40) | Converted OR to ln(OR) and 95% CI to SE of ln(OR) for analysis. Back-transformed OR is presented in forest plot. | ln(OR) (SE); 0.74 (0.25)
Welsh, 2005^96^; BMI ≥95% at baseline; 2–<3 drinks/d | 1y odds of overweight for 2–<3 sweet drinks/d vs. 0–<1 sweet drinks/d; OR (95% CI); 2.20 (1.40, 3.70) | Converted OR to ln(OR) and 95% CI to SE of ln(OR) for analysis. Back-transformed OR is presented in forest plot. | ln(OR) (SE); 0.79 (0.25)
Welsh, 2005^96^; BMI ≥95% at baseline; ≥3 drinks/d | 1y odds of overweight for ≥3 sweet drinks/d vs. 0–<1 sweet drinks/d; OR (95% CI); 1.80 (1.10, 2.90) | Converted OR to ln(OR) and 95% CI to SE of ln(OR) for analysis. Back-transformed OR is presented in forest plot. | ln(OR) (SE); 0.59 (0.25)
Wu, 2022^100^; All participants | 1y BMIZ for ≤4 oz/d sugary beverages vs. >4 oz/d; β (95% CI); −0.15 (−0.74, 0.43) | Effect estimate was multiplied by −1 to reflect a higher vs. lower intake comparison. | β (SE); 0.15 (0.30)
Wu, 2022^100^; Non-Hispanic participants | 1y BMIZ for ≤4 oz/d sugary beverages vs. >4 oz/d; β (95% CI); 0.19 (−0.71, 1.08) | Effect estimate was multiplied by −1 to reflect a higher vs. lower intake comparison. | β (SE); −0.19 (0.46)
Wu, 2022^100^; Hispanic participants | 1y BMIZ for ≤4 oz/d sugary beverages vs. >4 oz/d; β (95% CI); −0.37 (−1.09, 0.34) | Effect estimate was multiplied by −1 to reflect a higher vs. lower intake comparison. | β (SE); 0.37 (0.36)
Yiotaldiotariotam, 2013^102^; Change in BMI; SSB | 1y change in BMI per change in L/d SSB; β (95% CI); 0.10 (0.01, 0.13) | Converted 95% CI to SE.; Coefficients were converted from 1 L to 8 oz servings by multiplying estimates by 0.237. | β (SE); 0.02 (0.01)
Yiotaldiotariotam, 2013^102^; Change in BMI; Juice | 1y change in BMI per change in L/d fruit juice; β (95% CI); 0.23 (0.06, 0.43) | Converted 95% CI to SE.; Coefficients were converted from 1 L to 8 oz servings by multiplying estimates by 0.237. | β (SE); 0.05 (0.02)
Yiotaldiotariotam, 2013^102^; BMI; Soft drinks | 1y change in BMI per change in L/d soft drinks; β (95% CI); 0.15 (−0.25, 0.32) | Converted 95% CI to SE.; Coefficients were converted from 1 L to 8 oz servings by multiplying estimates by 0.237. | β (SE); 0.04 (0.03)
Yiotaldiotariotam, 2013^102^; BMI; SSB | 1y BMI per L/d SSB; β (SE); 0.137 (0.068) | BMI was converted to BMIZ using the LMS method. LMS values at 164.5 months were used and the average of Males and Females were calculated for the β and SE.; Coefficients were converted from 1 L to 8 oz servings by multiplying estimates by 0.237. | β (SE); 0.01 (0.01)
Yiotaldiotariotam, 2013^102^; BMI; Fruit juice | 1y BMI per L/d fruit juice; β (SE); 0.186 (0.164) | BMI was converted to BMIZ using the LMS method. LMS values at 164.5 months were used and the average of Males and Females were calculated for the β and SE.; Coefficients were converted from 1 L to 8 oz servings by multiplying estimates by 0.237. | β (SE); 0.02 (0.02)
Yiotaldiotariotam, 2013^102^; BMI; Soft drinks | 1y BMI per L/d soft drinks; β (SE); 0.142 (0.082) | BMI was converted to BMIZ using the LMS method. LMS values at 164.5 months were used and the average of Males and Females were calculated for the β and SE.; Coefficients were converted from 1 L to 8 oz servings by multiplying estimates by 0.237. | β (SE); 0.01 (0.01)
Yoon, 2022^103^; Q2 vs. Q1 | 1.2y BMIZ for 253 mL/d SSB vs. 100 mL/d; β (95% CI); 0.16 (−0.17, 0.49) | Converted 95% CI to SE. | β (SE); 0.16 (0.17)
Yoon, 2022^103^; Q3 vs. Q1 | 1.2y BMIZ for 376 mL/d SSB vs. 100 mL/d; β (95% CI); 0.09 (−0.25, 0.43) | Converted 95% CI to SE. | β (SE); 0.09 (0.17)
Yoon, 2022^103^; Q4 vs. Q1 | 1.2y BMIZ for 626 mL/d SSB vs. 100 mL/d; β (95% CI); 0.01 (−0.32, 0.35) | Converted 95% CI to SE. | β (SE); 0.01 (0.17)
Zhang, 2020^104^; OWO; 1–3 svg/wk | 2y odds of overweight/obesity for 1–3 svg/wk SSB vs. <1 svg/wk; β (SE); −0.08 (0.12) | Transformed to OR for presentation in forest plot. | ln(OR) (SE); −0.08 (0.12)
Zhang, 2020^104^; OWO; 4–6 svg/wk | 2y odds of overweight/obesity for 4–6 svg/wk SSB vs. <1 svg/wk; β (SE); −0.15 (0.20) | Transformed to OR for presentation in forest plot. | ln(OR) (SE); −0.15 (0.20)
Zhang, 2020^104^; OWO; ≥1 svg/d | 2y odds of overweight/obesity for ≥1 svg/wk SSB vs. <1 svg/wk; β (SE); −0.19 (0.23) | Transformed to OR for presentation in forest plot. | ln(OR) (SE); −0.19 (0.23)
Zheng, 2015^105^; CAPS; Change in BMI; TEI unadjusted | 3.5y change in BMIZ per 100 g/d SSB; β (SE); 0.08 (0.03) | Change in BMIZ was converted to change in BMI using the LMS method. LMS values at 138.5 months were used and the average of Males and Females were calculated for the β and SE.; Coefficients were converted to 8 oz svg/d by multiplying values by 2.47 (8 oz soda assumed to weigh ~246.6667 g). | β (SE); 0.49 (0.18)
Zheng, 2015^105^; CAPS; Change in BMI; TEI adjusted | 3.5y change in BMIZ per 100 g/d SSB; β (SE); 0.1 (0.03) | Change in BMIZ was converted to change in BMI using the LMS method. LMS values at 138.5 months were used and the average of Males and Females were calculated for the β and SE.; Coefficients were converted to 8 oz svg/d by multiplying values by 2.47 (8 oz soda assumed to weigh ~246.6667 g). | β (SE); 0.62 (0.18)
Zheng, 2015^105^; CAPS; Body Fat %; TEI unadjusted | 3.5y body fat percentage per 100 g/d SSB; β (SE); 0.92 (0.31) | Coefficients were converted to 8 oz svg/d by multiplying values by 2.47 (8 oz soda assumed to weigh ~246.6667 g). | β (SE); 2.28 (0.77)
Zheng, 2015^105^; CAPS; Body Fat %; TEI adjusted | 3.5y body fat percentage per 100 g/d SSB; β (SE); 1.04 (0.32) | Coefficients were converted to 8 oz svg/d by multiplying values by 2.47 (8 oz soda assumed to weigh ~246.6667 g). | β (SE); 2.58 (0.79)
Zheng, 2015^108^; EYHS; TEI unadjusted | 6y change in BMIZ per 100 g/d SSB; β (SE); 0.05 (0.02) | Coefficients were converted to 8 oz svg/d by multiplying values by 2.47 (8 oz soda assumed to weigh ~246.6667 g). | β (SE); 0.12 (0.05)
Zheng, 2015^108^; EYHS; TEI adjusted | 6y change in BMIZ per 100 g/d SSB; β (SE); 0.05 (0.02) | Coefficients were converted to 8 oz svg/d by multiplying values by 2.47 (8 oz soda assumed to weigh ~246.6667 g). | β (SE); 0.12 (0.05)
Zheng, 2015^106^; Healthy Start Study; TEI unadjusted | 1.5y change in BMIZ per 100 g/d sugary drinks; β (SE); 0.06 (0.03) | Change in BMIZ was converted to change in BMI using the LMS method. LMS values at 67.5 months were used and the average of Males and Females were calculated for the β and SE.; Coefficients were converted to 8 oz svg/d by multiplying values by 2.47 (8 oz soda assumed to weigh ~246.6667 g). | β (SE); 0.19 (0.10)
Zheng, 2015^106^; Healthy Start Study; TEI adjusted | 1.5y change in BMIZ per 100 g/d sugary drinks; β (SE); 0.05 (0.03) | Change in BMIZ was converted to change in BMI using the LMS method. LMS values at 67.5 months were used and the average of Males and Females were calculated for the β and SE.; Coefficients were converted to 8 oz svg/d by multiplying values by 2.47 (8 oz soda assumed to weigh ~246.6667 g). | β (SE); 0.16 (0.10)
Zheng, 2019^107^; OWO; TEI unadjusted | 8y odds of overweight/obesity per 100 g/d carbonated soft drinks; OR (95% CI); 1.10 (1.02, 1.18) | Converted OR to ln(OR) and 95% CI to SE of ln(OR) for analysis. Back-transformed OR is presented in forest plot.; Coefficients were converted to 8 oz svg/d by multiplying values by 2.47 (8 oz soda assumed to weigh ~246.6667 g). | ln(OR) (SE); 0.24 (0.09)
Zheng, 2019^107^; OWO; TEI adjusted | 8y odds of overweight/obesity per 100 g/d carbonated soft drinks; OR (95% CI); 1.10 (1.02, 1.18) | Converted OR to ln(OR) and 95% CI to SE of ln(OR) for analysis. Back-transformed OR is presented in forest plot.; Coefficients were converted to 8 oz svg/d by multiplying values by 2.47 (8 oz soda assumed to weigh ~246.6667 g). | ln(OR) (SE); 0.24 (0.09)
Zheng, 2019^107^; Change in BMI; Continuous intake | 8y change in BMI per 100 g/d carbonated soft drinks; β (95% CI); 0.19 (0.04, 0.33) | Converted 95% CI to SE. | β (SE); 0.47 (0.18)
Zheng, 2019^107^; Change in BMI; Categorical intake; ≤1/d | 8y change in BMI for ≤1 carbonated soft drink/d vs. none; β (95% CI); 0.32 (−1.27, 1.9) | Converted 95% CI to SE. | β (SE); 0.32 (0.81)
Zheng, 2019^107^; Change in BMI; Categorical intake; >1/d | 8y change in BMI for >1 carbonated soft drink/d vs. none; β (95% CI); 2.00 (0.32, 3.67) | Converted 95% CI to SE. | β (SE); 2.00 (0.85)
Zulfiqar, 2019^110^; Males | 6.3y odds of overweight/obesity for ≥1 SSB/d vs. none; OR (95% CI); 1.01 (0.80, 1.29) | Converted OR to ln(OR) and 95% CI to SE of ln(OR) for analysis. Back-transformed OR is presented in forest plot. | ln(OR) (SE); 0.01 (0.12)
Zulfiqar, 2019^110^; Females | 6.3y odds of overweight/obesity for ≥1 SSB/d vs. none; OR (95% CI); 1.08 (0.87, 1.35) | Converted OR to ln(OR) and 95% CI to SE of ln(OR) for analysis. Back-transformed OR is presented in forest plot. | ln(OR) (SE); 0.08 (0.11)

### Change in SSB and change in BMI in children

#### Continuous SSB intake

In addition to the main analysis reported in Table 5 and in Figure 3, the following subgroup analyses for change in SSB (continuous) and change in BMI in children were conducted: by sex (Figure A 1), by total energy intake (Figure A 2), by baseline weight status (Figure A 3), by juice content (Figure A 4) and by time between exposure and outcome assessment (Figure A 5). A subgroup analysis by age at exposure was not possible due to lack of variation in the evidence. Subgroup analyses were consistent with the main analysis and did not reveal statistically significant moderators. Specifically, the relationship did not differ by sex, TEI adjustment, baseline weight status, whether juice was included in the exposure group, or the time between exposure and outcome assessment, except that children with overweight and/or obesity at baseline had a greater increase in BMI over time than children with any BMI status at baseline.

Figure A 1 Meta-analysis of change in SSB (continuous, 8 oz/d) and change in BMI in children, by sex*

* BMI: body mass index; CI: confidence interval; d: day; ML: multilevel; oz: ounce; SSB: sugar-sweetened beverage; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of change in SSB (measured continuously, per 8 oz/d intake) and change in BMI in children, by sex. Overall, there is an increase in BMI in children with each additional increase of 8 oz/d SSB. The plot shows that results in only females or only in males do not significantly differ from those in mixed samples. The subgroups in males and in all children trended in the same direction, but the 95% CI crosses 0.

Figure A 2 Meta-analysis of change in SSB (continuous, 8 oz/d) and change in BMI in children, by TEI*

* Adj: adjusted; BMI: body mass index; CI: confidence interval; d: day; ML: multilevel; oz: ounce; PI: prediction interval; PI: prediction interval; SSB: sugar-sweetened beverage; TEI: total energy intake; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of change in SSB (measured continuously, per 8 oz/d intake) and change in BMI in children, by TEI adjustment. The plot shows that results adjusting for TEI do not significantly differ from those that do not adjust for TEI. In both subgroups, there is an increase in BMI in children with each additional increase of 8 oz/d SSB.

Figure A 3 Meta-analysis of change in SSB (continuous, 8 oz/d) and change in BMI in children, by baseline weight status*

* percentile: percentile; BMI: body mass index; CI: confidence interval; d: day; ML: multilevel; OWO: overweight and/or obesity; oz: ounce; SSB: sugar-sweetened beverage; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of change in SSB (measured continuously, per 8 oz/d intake) and change in BMI in children, by baseline weight status. The plot shows that results for participants with OWO and those without OWO do not significantly differ from those with any weight status. In the “With OWO” and “Without OWO” subgroups, the 95% CI crosses 0; in the “Any weight status” subgroup, there is a statistically significant increase in BMI in children with each additional increase of 8 oz/d SSB.

Figure A 4 Meta-analysis of change in SSB (continuous, 8 oz/d) and change in BMI in children, by juice content*

* BMI: body mass index; CI: confidence interval; d: day; ML: multilevel; oz: ounce; SSB: sugar-sweetened beverage; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of change in SSB (measured continuously, per 8 oz/d intake) and change in BMI in children, by juice content. The plot shows that results that include juice in the SSB measure do not significantly differ from those that do not report including juice. In the subgroup including fruit juice, there is an increase in BMI in children with each additional increase of 8 oz/d SSB; in the subgroup that did not report including juice, the results trend in the same direction, but the 95% CI crosses zero.

Figure A 5 Meta-analysis of change in SSB (continuous, 8 oz/d) and change in BMI in children, by duration between exposure and outcome assessment*

* BMI: body mass index; CI: confidence interval; d: day; f/u: follow-up; ML: multilevel; oz: ounce; PI: prediction interval; PI: prediction interval; SSB: sugar-sweetened beverage; y: year; vertical dotted line shows null effect

This figure shows a forest plot that demonstrates that the duration between exposure and outcome assessment is not associated with the relationship between change in SSB (measured continuously, per 8 oz/d intake) and change in BMI in children.

The contoured funnel plot of meta-analysis of change in SSB (continuous, 8 oz/d) and change in BMI in children is depicted in Figure A 6. The trim and fill method suggests 4 missing studies (2 of which may have significant effects), indicating potential publication bias. Egger’s test showed significant asymmetry (p = 0.001), which may indicate non-reporting bias or heterogeneity in the 19 effects. This is consistent with Figure 3.

Figure A 6 Contoured funnel plot of slopes for change in SSB (continuous, 8 oz/d) and change in BMI in children*

* BMI: body mass index; d: day; mo: month; oz: ounce; SSB: sugar-sweetened beverage

This figure shows a contoured funnel plot summarizing the meta-analysis of change in SSB (measured continuously, per 8 oz/d intake) and change in BMI in children. The plot shows 4 imputed studies with a range of standard errors and negative effect sizes. Two studies had p-values >0.05, one had p=0.05, and another had p=0.01.

#### Decrease in SSB intake versus no change or increase

In addition to themain analysis (https://gbc-word-edit.officeapps.live.com/we/wordeditorframe.aspx?ui=en-US&rs=en-US&wopisrc=https%3A%2F%2Fnih.sharepoint.com%2Fsites%2FORS-ORF-2025DGACTeam%2F_vti_bin%2Fwopi.ashx%2Ffiles%2F63aedf44ca2d4be7b6d63d9cd322b670&wdenableroaming=1&mscc=1&hid=689245A1-4006-6000-1CBE-F25EFC5FD754.0&uih=sharepointcom&wdlcid=en-US&jsapi=1&jsapiver=v2&corrid=f0463334-69dd-6ea8-23b9-a008d9620370&usid=f0463334-69dd-6ea8-23b9-a008d9620370&newsession=1&sftc=1&uihit=docaspx&muv=1&cac=1&sams=1&mtf=1&sfp=1&sdp=1&hch=1&hwfh=1&dchat=1&sc=%7B%22pmo%22%3A%22https%3A%2F%2Fnih.sharepoint.com%22%2C%22pmshare%22%3Atrue%7D&ctp=LeastProtected&rct=Normal&wdorigin=AuthPrompt.Sharing.DirectLink.Copy&instantedit=1&wopicomplete=1&wdredirectionreason=Unified_SingleFlush#_Meta-analysis) reported above (Table 5) and in Figure A 7, the subgroup analyses and meta-regressions for change in SSB intake (decrease in intake versus no change or increase in intake) and change in BMI in children are presented in Table A 6.

Figure A 7 Meta-analysis of change in SSB (categorical, decrease versus no change or increase in intake) and change in BMI in children*

* BMI: body mass index; c: cup; d: day; ML: multilevel; SEP: socioeconomic position; SSB: sugar-sweetened beverage; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of change in SSB (measured categorically as decrease in SSB intake versus no change or increase in intake) and change in BMI in children. Overall, there was not a statistically significant difference in the change in BMI among children who decreased SSB intake over time: 0.02 (95% CI: −0.14, 0.18).

Table A 15 Summary of subgroup analyses for change in SSB (categorical, decrease versus no change or increase in intake) and change in BMI in children^*^ * β: slope; BMI: body mass index; CI: confidence interval; mo: month; NA: not applicable; NR: not reported; OWO: overweight and/or obesity; ref: reference; SSB: sugar-sweetened beverage(s); TEI: total energy intake; vs: versus; y: year

Subgroup Analysis; Comparison | Test of Subgroup Differences; β (95% CI), p-value | Model Summary of Subgroup 1; β (95% CI), p-value | Model Summary of Subgroup 2; β (95% CI), p-value | Model Summary of Subgroup 3; β (95% CI), p-value
Age at Exposure; 2 up to 19y vs Birth up to 24mo (ref) | NA; (Only 2 up to 19y included) | NA | NA | NA
TEI; TEI adjusted vs Unadjusted (ref) | 0.03 (−0.49, 0.55), p=0.92 | [underlined: TEI unadjusted]; 0.03 (−0.20, 0.27), p=0.78 | [underlined: TEI adjusted]; NR (All data points from single study) | NA
Juice in SSB measure; Includes juice vs No juice reported (ref) | −0.20 (−0.51, 0.11), p=0.21 | [underlined: No juice reported]; 0.14 (−0.11, 0.40), p=0.27 | [underlined: Includes juice]; NR (All data points from single study) | NA
Sex; Females vs All (ref); Males vs All (ref) | NA; (No studies reported results by sex) | NA | NA | NA
Duration of follow-up; NA (time between baseline and follow-up modeled continuously) | NA; (all studies had ~2y duration) | NA | NA | NA
Baseline Weight Status; Without OWO vs Any (ref) | NA; (Only “Any” or unclear reported) | NA | NA | NA

#### Increase in SSB intake versus no change or decrease

In addition to the main analysis (https://gbc-word-edit.officeapps.live.com/we/wordeditorframe.aspx?ui=en-US&rs=en-US&wopisrc=https%3A%2F%2Fnih.sharepoint.com%2Fsites%2FORS-ORF-2025DGACTeam%2F_vti_bin%2Fwopi.ashx%2Ffiles%2F63aedf44ca2d4be7b6d63d9cd322b670&wdenableroaming=1&mscc=1&hid=689245A1-4006-6000-1CBE-F25EFC5FD754.0&uih=sharepointcom&wdlcid=en-US&jsapi=1&jsapiver=v2&corrid=f0463334-69dd-6ea8-23b9-a008d9620370&usid=f0463334-69dd-6ea8-23b9-a008d9620370&newsession=1&sftc=1&uihit=docaspx&muv=1&cac=1&sams=1&mtf=1&sfp=1&sdp=1&hch=1&hwfh=1&dchat=1&sc=%7B%22pmo%22%3A%22https%3A%2F%2Fnih.sharepoint.com%22%2C%22pmshare%22%3Atrue%7D&ctp=LeastProtected&rct=Normal&wdorigin=AuthPrompt.Sharing.DirectLink.Copy&instantedit=1&wopicomplete=1&wdredirectionreason=Unified_SingleFlush#_Meta-analysis) reported above (Table 5) and in Figure A 8, the subgroup analyses and meta-regressions for change in SSB intake (increase in intake versus no change or decrease in intake) and change in BMI in children are presented in Table A 7.

Figure A 8 Meta-analysis of change in SSB (categorical, increase versus no change or decrease in intake) and change in BMI in children*

* BMI: body mass index; c: cup; d: day; ML: multilevel; SEP: socioeconomic position; PI: prediction interval; PI: prediction interval; SSB: sugar-sweetened beverage; T#: tertile; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of change in SSB (measured categorically as increase in SSB intake versus no change or decrease in intake) and change in BMI in children. Overall, there is an increase of 0.12 (95% CI: 0.04, 0.19) in BMI among children who increased SSB intake over time.

Table A 16 Summary of subgroup analyses for change in SSB (categorical, increase versus no change or decrease in intake) and change in BMI in children^*^ * β: slope; BMI: body mass index; CI: confidence interval; mo: month; NA: not applicable; OWO: overweight and/or obesity; ref: reference; SSB: sugar-sweetened beverage(s); TEI: total energy intake; vs: versus; y: year

Subgroup Analysis; Comparison | Test of Subgroup Differences; β (95% CI), p-value | Model Summary of Subgroup 1; β (95% CI), p-value | Model Summary of Subgroup 2; β (95% CI), p-value | Model Summary of Subgroup 3; β (95% CI), p-value
Age at Exposure; 2 up to 19y vs; Birth up to 24mo (ref) | NA; (Only 2 up to 19y included) | NA | NA | NA
TEI; TEI adjusted vs Unadjusted (ref) | NA; (Only unadjusted included) | NA | NA | NA
Juice in SSB measure; Includes juice vs No juice reported (ref) | −0.34 (−0.89, 0.21), p=0.23 | [underlined: No juice reported]; NR (All data points from single study) | [underlined: Includes juice]; 0.11 (0.04, 0.18), p=0.003 | NA
Sex; Females vs All (ref); Males vs All (ref) | 0.24 (−0.05, 0.54), p=0.11; 0.01 (−0.30, 0.33), p=0.94 | [underlined: All]; 0.10 (0.02, 0.18), p=0.01 | [underlined: Females]; NR (All data points from single study) | [underlined: Males]; NR (All data points from single study)
Duration of follow-up; NA (time between baseline and follow-up modeled continuously) | 0.04 (−0.11, 0.18), p=0.61 | NA | NA | NA
Baseline Weight Status; Without OWO vs Any (ref) | −0.02 (−0.30, 0.26), p=0.89 | [underlined: Any]; 0.13 (−0.06, 0.32), p=0.19 | [underlined: Without OWO]; NR (All data points from single study) | NA

Egger’s test showed non-significant asymmetry (p = 0.15), which may indicate a lack of non-reporting bias or homogeneity (consistent with results in Figure A 8). The contoured funnel plot of meta-analysis of change in SSB (measured categorically) and change in BMI in children is depicted in Figure A 9. The trim and fill method suggests 2 missing studies (1 of which may be significant), indicating some potential publication bias.

Figure A 9 Contoured funnel plot of slopes for change in SSB (categorical, increase versus no change or decrease in intake) and change in BMI in children

This figure shows a contoured funnel plot summarizing the meta-analysis of change in SSB (measured categorically as increase in SSB intake versus no change or decrease in intake) and change in BMI in children. The plot shows 2 imputed studies with a range of standard errors and negative effect sizes. One study had p-values >0.10 and the other had p=0.05.

### RCT-SSB interventions and change in BMI in children

In addition to the main analysis reported above (Table 5) and in Figure A 10, the following subgroup analyses for SSB intervention and change in BMI in children were conducted: by total energy intake (Figure A 11), by baseline weight status (Figure A 12), and by juice content (Figure A 13). All studies were in children older than 24 months and no studies reported results by sex, so no subgroup analysis by age at exposure or by sex were conducted. A meta-regression of trial duration is reported in Figure A 14.

TEI adjustment was a statistically significant moderator, but only study adjusted for TEI. Subgroup analyses of baseline weight status and whether juice was included in the SSB exposure did not reveal significant differences between subgroups. Trial duration did not impact the relationship. Age group at exposure was not tested due to lack of variation; all studies included children age 2 to 19 years.

Figure A 10 Meta-analysis of SSB intervention and change in BMI in children*

* BMI: body mass index; CI: confidence interval; MD: mean difference; PI: prediction interval; RE: random effects; SSB: sugar-sweetened beverage; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of SSB intervention and change in BMI in children. Overall, interventions to decrease SSB intake resulted in 0.30 (95% CI: −0.52, −0.07) decreased BMI at follow-up.

Figure A 11 Meta-analysis of SSB intervention and change in BMI in children, by TEI*

* Adj: adjusted; BMI: body mass index; CI: confidence interval; MD: mean difference; PI: prediction interval; RE: random effects; SSB: sugar-sweetened beverage; TEI: total energy intake; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of SSB intervention and change in BMI in children, by TEI adjustment. The plot shows that results adjusting for TEI do not significantly differ from those that do not adjust for TEI. In both the TEI-adjusted and the TEI-unadjusted subgroups, interventions to decrease SSB intake resulted in decreased BMI at follow-up, but the relationship was stronger in the TEI-adjusted subgroup. Only one study adjusted for TEI.

Figure A 12 Meta-analysis of SSB intervention and change in BMI in children, by baseline weight status*

* BMI: body mass index; CI: confidence interval; MD: mean difference; OWO: overweight and/or obesity; PI: prediction interval; RE: random effects; SSB: sugar-sweetened beverage; T#: tertile; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of SSB intervention and change in BMI in children, by baseline weight status. The plot shows that results for participants without OWO or without OWO do not significantly differ from those with any weight status. In the “Without OWO” subgroup, the 95% CI crosses 0; in the “With OWO” subgroup, SSB interventions resulted in a statistically significant decrease in BMI. Only one study reported results for participants with any weight status at baseline.

Figure A 13 Meta-analysis of SSB intervention and change in BMI in children, by juice content*

* BMI: body mass index; CI: confidence interval; MD: mean difference; PI: prediction interval; RE: random effects; SSB: sugar-sweetened beverage; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of SSB intervention and change in BMI in children, by juice content. The plot shows that results that include juice in the SSB measure do not significantly differ from those that do not report including juice. Only one study included fruit juice.

Figure A 14 Meta-analysis of SSB intervention and change in BMI in children, by trial duration*

* BMI: body mass index; CI: confidence interval; f/u: follow-up; MD: mean difference; PI: prediction interval; SSB: sugar-sweetened beverage; vertical dotted line shows null effect

This figure shows a forest plot that demonstrates that the duration between exposure and outcome assessment is not associated with the relationship between SSB intervention and change in BMI in children.

### SSB intake at baseline and change in BMI in children

#### Continuous SSB intake

In addition to the main analysis reported in Table 5 and in Figure A 15, the following subgroup analyses for SSB intake at baseline and change in BMI in children were conducted: by sex (Figure A 16), by total energy intake (Figure A 17), by baseline weight status (Figure A 18), and by juice content (Figure A 19). No studies included children younger than 2 years, so no subgroup analysis by age at exposure was completed. Age at outcome assessment was examined in Figure A 20 and the meta-regression exploring duration between exposure and outcome assessment is reported in Figure A 21.

Figure A 15 Meta-analysis of SSB at baseline (continuous, 8 oz/d) and change in BMI in children*

* BMI: body mass index; CI: confidence interval; d: day; ML: multilevel; oz: ounce; SSB: sugar-sweetened beverage; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of SSB at baseline (measured continuously, per 8 oz/d intake) and change in BMI in children. Overall, there is an 0.09 (95% CI: 0.02, 0.16) increase in BMI with each additional 8 oz/d SSB.

Figure A 16 Meta-analysis of SSB at baseline (continuous, 8 oz/d) and change in BMI in children, by sex*

* BMI: body mass index; CI: confidence interval; d: day; ML: multilevel; oz: ounce; SSB: sugar-sweetened beverage; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of SSB at baseline (measured continuously, per 8 oz/d intake) and change in BMI in children, by sex. The plot shows that results in only females or only in males do not significantly differ from those in mixed samples. In the female and male subgroups, the 95% CI crosses 0; in the mixed subgroup, there is a statistically significant increase in BMI with each additional 8 oz/d SSB.

Figure A 17 Meta-analysis of SSB at baseline (continuous, 8 oz/d) and change in BMI in children, by TEI*

* Adj: adjusted; BMI: body mass index; CI: confidence interval; d: day; ML: multilevel; oz: ounce; PI: prediction interval; SSB: sugar-sweetened beverage; TEI: total energy intake; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of SSB at baseline (measured continuously, per 8 oz/d intake) and change in BMI in children, by TEI adjustment. The plot shows that results adjusting for TEI do not significantly differ from those that do not adjust for TEI. In both subgroups, there is an increase in BMI with each additional 8 oz/d SSB.

Figure A 18 Meta-analysis of SSB at baseline (continuous, 8 oz/d) and change in BMI in children, by baseline weight status*

* percentile: percentile; BMI: body mass index; CI: confidence interval; d: day; ML: multilevel; OWO: overweight and/or obesity; oz: ounce; PI: prediction interval; SSB: sugar-sweetened beverage; y: year; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of SSB at baseline (measured continuously, per 8 oz/d intake) and change in BMI in children, by baseline weight status. The plot shows that results for participants without OWO do not significantly differ from those with any weight status. In the “With OWO” subgroup, the 95% CI crosses 0; in the “Any weight status” subgroup, there is a statistically significant increase in BMI with each additional 8 oz/d SSB. Only one study reported results for participants with OWO at baseline.

Figure A 19 Meta-analysis of SSB at baseline (continuous, 8 oz/d) and change in BMI in children, by juice content*

* BMI: body mass index; CI: confidence interval; d: day; ML: multilevel; oz: ounce; SSB: sugar-sweetened beverage; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of SSB at baseline (measured continuously, per 8 oz/d intake) and change in BMI in children, by juice content. The plot shows that results that include juice in the SSB measure do not significantly differ from those that do not report including juice. In both subgroups the 95% CI crosses zero.

Figure A 20 Meta-analysis of SSB at baseline (continuous, 8 oz/d) and change in BMI in children, by age at outcome*

* BMI: body mass index; CI: confidence interval; d: day; ML: multilevel; oz: ounce; PI: prediction interval; SSB: sugar-sweetened beverage; y: year; vertical dotted line shows null effect

This figure shows the same information as in the main analysis (Figure 19) and adds results for change in BMI in adulthood. Results with the outcome in adults also showed that there is a statistically significant increase in BMI of 0.42 (95% CI: 0.13, 0.72) with each additional 8 oz/d SSB.

Figure A 21 Meta-analysis of SSB at baseline (continuous, 8 oz/d) and change in BMI in children, by duration between exposure and outcome assessment*

* BMI: body mass index; CI: confidence interval; d: day; f/u: follow-up; ML: multilevel; oz: ounce; PI: prediction interval; SSB: sugar-sweetened beverage; y: year; vertical dotted line shows null effect

This figure shows a forest plot that demonstrates that the duration between exposure and outcome assessment is not associated with the relationship between SSB at baseline (measured continuously, per 8 oz/d intake) and change in BMI in children.

Egger’s test showed significant asymmetry (p=0.004), which may indicate non-reporting bias or heterogeneity (which is consistent with Figure A 15). The contoured funnel plot of the meta-analysis of SSB intake at baseline (continuous, 8 oz/d) and change in BMI in children is presented in Figure A 22. The trim and fill method suggests that no studies are missing.

Figure A 22 Contoured funnel plot of slopes for SSB at baseline (continuous, 8 oz/d) and change in BMI in children

This figure shows a contoured funnel plot summarizing the meta-analysis of SSB intake at baseline (measured continuously, per 8 oz/d intake) and change in BMI in children. The plot shows 0 imputed studies.

#### Any SSB intake versus rare or no intake

The main analysis for SSB intake at baseline (measured categorically as any SSB intake versus rare or no SSB intake) and change in BMI in children is presented in Figure A 23. Subgroup analyses are presented in Table A 8. Age at outcome assessment was also examined (Figure A 24).

A statistically significant difference was found by whether fruit juice was included in the SSB measure, but only one study included juice. Neither TEI adjustment nor duration between exposure and outcome assessment altered the results. Subgroup analyses by age group at exposure or by weight status at baseline were not completed due to lack of variation.

Figure A 23 Meta-analysis of SSB at baseline (categorical, any versus rare or no intake) and change in BMI in children*

* BMI: body mass index; CI: confidence interval; d: day; g: gram; ML: multilevel; mo: month; oz: ounce; PI: prediction interval; SSB: sugar-sweetened beverage; svg: serving; wk: week; vs: versus; y: year; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of SSB at baseline (measured categorically as any SSB intake versus rare or no intake) and change in BMI in children. Overall, there was not a statistically significant difference in the change in BMI by SSB intake: 0.07 (95% CI: −0.01, 0.14).

Table A 17 Summary of subgroup analyses for SSB at baseline (categorical, any versus rare or no intake) and change in BMI in children^†^ † β: slope; BMI: body mass index; CI: confidence interval; mo: month; NA: not applicable; NR: not reported; OWO: overweight and/or obesity; ref: reference; SSB: sugar-sweetened beverage(s); TEI: total energy intake; vs: versus; y: year

Subgroup Analysis; Comparison | Test of Subgroup Differences; β (95% CI), p-value | Model Summary of Subgroup 1; β (95% CI), p-value | Model Summary of Subgroup 2; β (95% CI), p-value
Age at Exposure; 2 up to 19y vs Birth up to 24mo (ref) | (Only 2 up to 19y included); NA | NA | NA
Sex; Females vs All (ref); Males vs All (ref) | NA; (No studies reported results by sex) | NA | NA
TEI; TEI adjusted vs Unadjusted (ref) | 0.10 (−0.01, 0.21), p=0.08 | [underlined: TEI unadjusted]; 0.02 (−0.05, 0.09), p=0.50 | [underlined: TEI adjusted]; 0.57 (−0.51, 1.66), p=0.30
Baseline Weight Status; Without OWO vs Any (ref) | NA; (Only “Any” or unclear reported) | NA | NA
Juice in SSB measure; Includes juice vs No juice reported (ref) | −0.12 (−0.23, −0.02), p=0.02 | [underlined: No juice reported]; 0.10 (0.05, 0.15), p<0.01 | [underlined: Includes juice]; NR (All data points from single study)
Duration of follow-up; NA (time between baseline and follow-up modeled continuously) | 0.007 (−0.05, 0.07), p=0.81 | NA | NA

Figure A 24 Meta-analysis of SSB at baseline (categorical, any versus rare or no intake) and change in BMI, by age at outcome*

* BMI: body mass index; CI: confidence interval; d: day; g: gram; ML: multilevel; mo: month; oz: ounce; PI: prediction interval; SSB: sugar-sweetened beverage; svg: serving; wk: week; vs: versus; y: year; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of SSB at baseline (measured categorically as any SSB intake versus rare or no intake) and change in BMI in children, by age at outcome assessment. Results with the outcome in adults showed that there is a statistically significant increase in BMI of 0.89 (95% CI: 0.38, 1.39) with any SSB intake.

Egger’s test showed significant asymmetry (p=0.003), which may indicate non-reporting bias. The contoured funnel plot of the meta-analysis of SSB at baseline (measured categorically, any SSB intake versus rare or no SSB intake) and change in BMI in children is presented in Figure A 25. The trim and fill method suggests that 2 studies may be missing. The asymmetry could be due to non-reporting bias.

Figure A 25 Contoured funnel plot of slopes for SSB at baseline (categorical, any versus rare or no intake) and change in BMI in children

This figure shows a contoured funnel plot summarizing the meta-analysis of SSB at baseline (measured categorically as any SSB intake versus rare or no intake) and change in BMI in children. The plot shows 2 imputed studies with moderate or large standard errors and negative effect sizes. One study had a p-value >0.05 and one had p=0.05.

#### Some SSB intake versus less intake

The main analysis for SSB intake at baseline (measured categorically as some SSB intake versus less SSB intake) and change in BMI in children is shown in (Figure A 26). Additional analyses were conducted by age at exposure, by baseline weight status, by juice content and by duration between exposure and outcome assessment (Table A 9).

The subgroup analyses do not change the interpretation of the main analysis. A statistically significant difference by age group at exposure was found, but only one study was conducted in children younger than 24 months. No statistically significant differences were found between subgroups by baseline weight status, juice content in the SSB exposure, or duration between exposure and outcome assessments. Subgroup analyses by age group at outcome or TEI-adjustment were not completed due to lack of variation.

Figure A 26 Meta-analysis of SSB at baseline (categorical, some versus less intake) and change in BMI in children*

* BMI: body mass index; CI: confidence interval; d: day; g: gram; ML: multilevel; mo: month; oz: ounce; PI: prediction interval; SSB: sugar-sweetened beverage; svg: serving; wk: week; vs: versus; y: year; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of SSB at baseline (measured categorically as some SSB intake versus less intake) and change in BMI in children. Overall, there was not a statistically significant difference in the change in BMI by SSB intake: 0.14 (95% CI: −0.01, 0.30).

Table A 18 Summary of subgroup analyses for SSB at baseline (categorical, some versus less intake) and change in BMI in children^*^ * β: slope; BMI: body mass index; CI: confidence interval; mo: month; NA: not applicable; NR: not reported; OWO: overweight and/or obesity; ref: reference; SSB: sugar-sweetened beverage(s); TEI: total energy intake; vs: versus; y: year

Subgroup Analysis; Comparison | Test of Subgroup Differences; β (95% CI), p-value | Model Summary of Subgroup 1; β (95% CI), p-value | Model Summary of Subgroup 2; β (95% CI), p-value | Model Summary of Subgroup 3; β (95% CI), p-value
Age at Exposure; 2 up to 19y vs Birth up to 24mo (ref) | 0.52 (0.29, 0.76), p<0.01 | [underlined: Birth up to 24mo]; NR (All data points from single study) | [underlined: 2 up to 19y]; 0.16 (−0.02, 0.35), p=0.09 | NA
Sex; Females vs All (ref); Males vs All (ref) | NA; (No studies reported results by sex) | NA | NA | NA
TEI; TEI adjusted vs Unadjusted (ref) | NA; (No studies reported adjusted results) | NA | NA | NA
Baseline Weight Status; Without OWO vs Any (ref); Unknown vs Any (ref) | −0.19 (−0.56, 0.19), p=0.33; 0.12 (−0.25, 0.50), p=0.52 | [underlined: Any]; NR (All data points from single study) | [underlined: Without OWO]; NR (All data points from single study) | [underlined: Unknown]; NR (All data points from single study)
Juice in SSB measure; Includes juice vs No juice reported (ref) | −0.04 (−0.42, 0.35), p=0.86 | [underlined: No juice reported]; 0.16 (−0.07, 0.38), p=0.17 | [underlined: Includes juice]; 0.12 (−0.16, 0.41), p=0.40 | NA
Duration of follow-up; NA (time between baseline and follow-up modeled continuously) | 0.03 (−0.09, 0.14), p=0.64 | NA | NA | NA

Egger’s test did not show significant asymmetry (p = 0.22), which is consistent with a lack of non-reporting bias (i.e., homogeneity). The contoured funnel plot of the meta-analysis of SSB at baseline (measured categorically, some SSB intake versus less SSB intake) and change in BMI in children is presented in Figure A 27. The trim and fill method suggests 4 missing studies, including 1 significant study, which indicates a small amount of potential publication bias given the 24 observed slopes.

Figure A 27 Contoured funnel plot of slopes for SSB at baseline (categorical, some versus less intake) and change in BMI in children

This figure shows a contoured funnel plot summarizing the meta-analysis of SSB at baseline (measured categorically as some versus less SSB intake) and change in BMI in children. The plot shows 4 imputed studies with moderate standard errors and negative effect sizes. Three studies had p-values >0.10 and one had p=0.05.

### SSB intake at baseline and risk of obesity at follow-up during childhood

#### Continuous SSB intake

In addition to the main analysis reported in Table 5 and in Figure A 28, the following subgroup analyses for SSB intake at baseline (continuously) and risk of overweight and/or obesity at follow-up during childhood were conducted: TEI and baseline weight status (Figure A 29) and by duration of follow-up (Figure A 30).

Both TEI adjustment and baseline weight status significantly moderated the association; studies that adjusted for TEI and participants without overweight or obesity at baseline had higher odds of overweight and/or obesity at follow-up compared to studies that did not adjust for TEI and participants with any weight status at baseline. However, because all observations that adjusted for TEI were in participants who did not have overweight or obesity at baseline, it is not possible to distinguish between the impact or TEI adjustment and baseline weight status.

Figure A 28 Meta-analysis of SSB at baseline (continuous, 8 oz/d) and overweight and/or obesity at follow-up in children*

* CI: confidence interval; d: day; ML: multilevel; OR: odds ratio; OWO: overweight/obesity; oz: ounce; PI: prediction interval; SSB: sugar-sweetened beverage; y: year; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of SSB at baseline (measured continuously, per 8 oz/d intake) and risk of overweight and/or obesity at follow-up in children. Overall, there was not a statistically significant difference in the odds of overweight and/or obesity by SSB intake: 1.13 (95% CI: 0.97, 1.31).

Figure A 29 Meta-analysis of SSB at baseline (continuous, 8 oz/d) and overweight and/or obesity at follow-up in children, by TEI and baseline weight status*

* CI: confidence interval; d: day; ML: multilevel; OR: odds ratio; OWO: overweight/obesity; oz: ounce; PI: prediction interval; SSB: sugar-sweetened beverage; TEI: total energy intake; y: year; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of SSB at baseline (measured continuously, per 8 oz/d intake) and risk of overweight and/or obesity at follow-up in children, by TEI adjustment and baseline weight status. In both the TEI-adjusted and without OWO subgroup and the TEI-unadjusted and any weight status subgroup, the odds of overweight and/or obesity was higher with greater SSB intake, but the relationship was stronger in the TEI-adjusted and without OWO subgroup.

Figure A 30 Meta-analysis of SSB at baseline (continuous, 8 oz/d) and overweight and/or obesity at follow-up in children, by duration between exposure and outcome assessment*

* CI: confidence interval; d: day; f/u: follow-up; ML: multilevel; OR: odds ratio; OWO: overweight/obesity; oz: ounce; PI: prediction interval; SSB: sugar-sweetened beverage; y: year; vertical dotted line shows null effect

This figure shows a forest plot that demonstrates that the duration between exposure and outcome assessment is not associated with the relationship between SSB at baseline (measured continuously, per 8 oz/d intake) and risk of overweight and/or obesity at follow-up in children.

#### Any SSB intake versus no intake

The main analysis for SSB intake at baseline (measured categorically, any SSB intake versus no SSB intake) and risk of overweight and/or obesity at follow-up during childhood is depicted in Figure A 31. The subgroup analyses were conducted and are summarized in Table A 10. Mean effects differed significantly between subgroups by presence of juice in the SSB exposure and by sex. However, the only study that separately examined males and females was also the only study to explicitly include juice in the SSB measure. Thus, it is not possible to disentangle the individual effects of sex and juice content (i.e., the factors are confounded). Age at exposure significantly moderated the association between baseline SSB intake and odds of overweight and/or obesity. Specifically, the association was stronger in infants and young children up to age 24 months compared to children and adolescents aged 2 to 19 years. TEI adjustment and duration of follow-up did not significantly moderate the association.

Figure A 31 Meta-analysis of SSB at baseline (categorical, any versus none) and overweight and/or obesity at follow-up in children*

* CI: confidence interval; d: day; ML: multilevel; OB: obesity; OR: odds ratio; OW: overweight; oz: ounce; PI: prediction interval; SSB: sugar-sweetened beverage; vs: versus; x: times; y: year; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of SSB at baseline (measured categorically as any SSB intake versus no intake) and risk of overweight and/or obesity at follow-up in children. Overall, the odds of overweight and/or obesity at follow-up is greater with any SSB intake: 1.40 (95% CI: 1.04, 1.89).

Table A 19 Summary of subgroup analyses for SSB at baseline (categorical, any versus none) and overweight and/or obesity at follow-up in children^*^ * CI: confidence interval; FU: follow-up; mo: month; NA: not applicable; NR: not reported; OR: odds ratio; OWO: overweight and/or obesity; ref: reference; SSB: sugar-sweetened beverage(s); TEI: total energy intake; vs: versus; y: year

Subgroup Analysis; Comparison | Test of Subgroup Differences; OR (95% CI), p-value | Model Summary of Subgroup 1; OR (95% CI), p-value | Model Summary of Subgroup 2; OR (95% CI), p-value | Model Summary of Subgroup 3; OR (95% CI), p-value
Age at Exposure; 2 up to 19y vs Birth up to 24mo (ref) | 0.59 (0.41, 0.86), p=0.005 | [underlined: Up to 24mo]; 1.84 (1.32, 2.56), p=0.0003 | [underlined: 2 up to 19y]; 1.12 (0.90, 1.39), p=0.32 | NA
Sex; Females vs All (ref); Males vs All (ref) | 0.67 (0.48, 0.93), p=0.02; 0.62 (0.44, 0.88), p=0.01 | [underlined: All]; 1.62 (1.26, 2.09), p=0.0002 | [underlined: Females]^*^; NR (All data points from single study) | [underlined: Males]^*^; NR (All data points from single study)
TEI; TEI adjusted vs Unadjusted (ref) | 0.94 (0.41, 2.16), p=0.88 | [underlined: TEI unadjusted]; 1.45 (0.96, 2.19). p=0.08 | [underlined: TEI adjusted]; NR (All data points from single study) | NA
Juice in SSB measure; Includes juice vs No juice reported (ref) | 0.65 (0.48, 0.87), p=0.004 | [underlined: No juice reported]; 1.62 (1.26, 2.09), p=0.0002 | [underlined: Includes juice]^†^; † Only one study included juice in measure of SSB; this study was also the only one to examine males and females separately; NR (All data points from single study) | NA
Baseline Weight Status | NA; All studies included “Any” or “Unclear” status | NA | NA | NA
Duration of Follow-up; NA (time between baseline and follow-up modeled continuously) | 0.92 (0.80, 1.07), p=0.29 | NA | NA | NA

#### More SSB intake versus less intake

The main analysis for SSB intake at baseline (measured categorically, more SSB intake versus less SSB intake) and risk of overweight and/or obesity at follow-up during childhood were conducted is depicted below (Figure A 32). The subgroup analyses were conducted and presented in Table A 11.

The relationship was stronger in populations exclusively with overweight/obesity or exclusively without overweight/obesity compared to populations that included participants with any weight status. However, only one study had an analysis exclusively among participants with OWO. Age at exposure, TEI adjustment, juice, sex, and duration of follow-up did not moderate the association.

Figure A 32 Meta-analysis of SSB at baseline (categorical, more versus less intake) and overweight and/or obesity at follow-up in children*

* BMI: body mass index; CI: confidence interval; d: day; f/u: follow-up; med: median; ML: multilevel; mL: mililiter; OR: odds ratio; OW: overweight; oz: ounce; PI: prediction interval; Q: quartile; SSB: sugar-sweetened beverage; svg: serving; T: tertile; vs: versus; wk: week; x: times; y: year; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of SSB at baseline (measured categorically as more SSB intake versus less) and risk of overweight and/or obesity at follow-up in children. Overall, the odds of overweight and/or obesity at follow-up is greater with some SSB intake: 1.42 (95% CI: 1.15, 1.75).

Table A 20 Summary of subgroup analyses for SSB at baseline (categorical, more versus less intake) and overweight and/or obesity at follow-up in children^*^ * CI: confidence interval; FU: follow-up; mo: month; NA: not applicable; NR: not reported; OR: odds ratio; OWO: overweight and/or obesity; ref: reference; SSB: sugar-sweetened beverage(s); TEI: total energy intake; vs: versus; y: year

Subgroup Analysis; Comparison | Test of Subgroup Differences; OR (95% CI), p-value | Model Summary of Subgroup 1; OR (95% CI), p-value | Model Summary of Subgroup 2; OR (95% CI), p-value | Model Summary of Subgroup 3; OR (95% CI), p-value | Model Summary of Subgroup 4; OR (95% CI), p-value
Age at Exposure; 2 up to 19y vs Birth up to 24mo (ref) | 1.33 (0.69, 2.55), p=0.40 | [underlined: Up to 24mo]; NR (All data points from single study) | [underlined: 2 up to 19y]; 1.47 (1.17, 1.85), p=0.001 | NA | NA
Sex; Females vs All (ref); Males vs All (ref) | 0.95 (0.55, 1.63), p=0.84; 0.75 (0.40, 1.40), p=0.36 | [underlined: All]; 1.46 (1.13, 1.87), p=0.03 | [underlined: Females]; 1.32 (0.998, 1.751), p=0.05 | [underlined: Males]; NR (All data points from single study) | NA
TEI; TEI adjusted vs Unadjusted (ref) | 1.21 (0.80, 1.85), p=0.37 | [underlined: TEI unadjusted]; 1.21 (0.93, 1.83), p=0.12 | [underlined: TEI adjusted]; 1.55 (1.21, 1.99), p=0.001 | NA | NA
Juice in SSB measure; Includes juice vs No juice reported (ref) | 0.76 (0.51, 1.12), p=0.17 | [underlined: No juice reported]; 1.53 (1.14, 2.06), p=0.005 | [underlined: Includes juice]; 1.26 (0.97, 1.65), p=0.08 | NA | NA
Baseline Weight Status; With OWO vs Any (ref); Without OWO vs Any (ref); Unknown vs Any (ref) | 1.97 (1.19, 3.27), p=0.009; 1.66 (1.08, 2.56), p=0.02; 1.21 (0.79, 1.83), p=0.38 | [underlined: Any]; 1.16 (0.95, 1.43), p=0.17 | [underlined: With OWO]; NR (All data points from single study) | [underlined: Without OWO]; 1.96 (1.33, 2.90), p=0.001 | [underlined: Unknown]; 1.45 (0.97, 2.17), p=0.07
Duration of Follow-up; NA (time between baseline and follow-up modeled continuously) | 1.004 (0.94, 1.07), p=0.89 | NA | NA | NA | NA

The contoured funnel plot of the meta-analysis for SSB intake at baseline (measured categorically, more SSB intake versus less SSB intake) and risk of overweight and/or obesity (OWO) at follow-up during childhood is depicted in Figure A 33. Egger’s test showed significant asymmetry (p=0.02), which may indicate non-reporting bias or heterogeneity, consistent with the moderate heterogeneity seen in Figure A 32 and supported by the analysis of the role of baseline weight status. Five potentially missing studies with odds ratio less than 1 were identified by the trim and fill analysis.

Figure A 33 Contoured funnel plot of odds ratios SSB intake at baseline (categorical, more SSB intake versus less SSB intake) overweight and/or obesity at follow-up in children

This figure shows a contoured funnel plot summarizing the meta-analysis of SSB at baseline (measured categorically as more SSB intake versus no less) and risk of overweight and/or obesity at follow-up in children. The plot shows 5 imputed studies with moderate or large standard errors and negative effect sizes. Three studies had p-values >0.10, one had p=0.10 and one had p=0.05.

### SSB intake at baseline and risk of obesity follow-up during adulthood

#### Continuous SSB intake

In addition to the main analysis shown below (Figure A 34), the following subgroup analyses for SSB intake at baseline (continuous) and risk of obesity during adulthood were conducted: by sex (Figure A 35), by total energy intake (Figure A 36), by baseline weight status (Figure A 37), and by duration between exposure and outcome assessment (Figure A 38). No subgroup analyses revealed statistically significant moderators, although it was not possible to conduct subgroup analyses by age group at exposure or by whether juice was included in the exposure group due to lack of variation.

Figure A 34 Meta-analysis of SSB at baseline (continuous, 8 oz/d) and overweight and/or obesity at follow-up during adulthood*

* CI: confidence interval; d: day; f/u: follow-up; ML: multilevel; oz: ounce; PI: prediction interval; SSB: sugar-sweetened beverage; y: year; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of SSB at baseline (measured continuously, per 8 oz/d intake) and risk of overweight and/or obesity at follow-up in adulthood. Overall, there was not a statistically significant difference in the odds of overweight and/or obesity by SSB intake: 1.14 (95% CI: 0.97, 1.33).

Figure A 35 Meta-analysis of SSB at baseline (continuous, 8 oz/d) and overweight and/or obesity at follow-up during adulthood, by sex*

* CI: confidence interval; d: day; ML: multilevel; oz: ounce; PI: prediction interval; SSB: sugar-sweetened beverage; y: year; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of SSB at baseline (measured continuously, per 8 oz/d intake) and risk of overweight and/or obesity at follow-up in adulthood, by sex. The plot shows that results in only females or only in males do not significantly differ from those in mixed samples.

Figure A 36 Meta-analysis of SSB at baseline (continuous, 8 oz/d) and overweight and/or obesity at follow-up during adulthood, by TEI*

* CI: confidence interval; d: day; f/u: follow-up; g: gram; ML: multilevel; mo: month; oz: ounce; PI: prediction interval; SSB: sugar-sweetened beverage; svg: serving; wk: week; y: year; TEI: total energy intake; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of SSB at baseline (measured continuously, per 8 oz/d intake) and risk of overweight and/or obesity at follow-up in adulthood, by TEI adjustment. The plot shows that results adjusting for TEI do not significantly differ from those that do not adjust for TEI. In the TEI adjusted subgroup, odds of overweight and/or obesity at follow-up is higher with greater SSB intake: 1.19 (95% CI: 1.10, 1.30). The TEI-unadjusted results trended in the same direction, but the 95% CI crosses 0.

Figure A 37 Meta-analysis of SSB at baseline (continuous, 8 oz/d) and overweight and/or obesity at follow-up during adulthood, by baseline weight status*

* CI: confidence interval; d: day; f/u: follow-up; ML: multilevel; mo: month; OWO: overweight and/or obesity; oz: ounce; PI: prediction interval; SSB: sugar-sweetened beverage; y: year; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of SSB at baseline (measured continuously, per 8 oz/d intake) and risk of overweight and/or obesity at follow-up in adulthood, by baseline weight status. The plot shows that results among those without OWO at baseline do not significantly differ from those with any weight status. A pooled estimate of the without OWO group was not calculated because all results were from the same study.

Figure A 38 Meta-analysis of SSB at baseline (continuous, 8 oz/d) and overweight and/or obesity at follow-up during adulthood, by duration between exposure and outcome assessment*

* CI: confidence interval; d: day; f/u: follow-up; ML: multilevel; mo: month; oz: ounce; PI: prediction interval; SSB: sugar-sweetened beverage; y: year; vertical dotted line shows null effect

This figure shows a forest plot that demonstrates that the duration between exposure and outcome assessment is not associated with the relationship between SSB at baseline (measured continuously, per 8 oz/d intake) and risk of overweight and/or obesity at follow-up in adulthood.

### SSB at baseline and BMI z-score at follow-up in children

#### Continuous SSB intake

In addition to the main analysis (Figure A 39), the following subgroup analyses were conducted for SSB at baseline and BMI z-score at follow-up in children: by age at exposure (Figure A 40), by sex (Figure A 41), by total energy intake (Figure A 42), by baseline weight status (Figure A 43), by juice content (Figure A 44). Age at outcome (Figure A 45) and duration between exposure and outcome assessment were also examined (Figure A 46).

Duration between exposure and outcome assessment did not moderate the association. None of the subgroup analyses showed significant differences, although only one study included measures of BMI z-score in adulthood.

Figure A 39 Meta-analysis of SSB at baseline (continuous, 8 oz/d) and BMI z-score at follow-up in children*

* BMI z-score: body mass index z-score; CI: confidence interval; d: day; mo: month; ML: multilevel; oz: ounce; PI: prediction interval; PI: prediction interval; SSB: sugar-sweetened beverage; y: year; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of SSB at baseline (measured continuously, per 8 oz/d intake) and BMI z-score at follow-up in children. Overall, BMI z-score at follow-up is 0.04 (95% CI: 0.00, 0.08) greater with each additional 8 oz/d SSB.

Figure A 40 Meta-analysis of SSB at baseline (continuous, 8 oz/d) and BMI z-score at follow-up in children, by age at exposure*

* BMI z-score: body mass index z-score; ChildAdol: children and adolescents age 2 to 19 y; CI: confidence interval; d: day; mo: month; ML: multilevel; oz: ounce; PI: prediction interval; SSB: sugar-sweetened beverage; y: year; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of SSB at baseline (measured continuously, per 8 oz/d intake) and BMI z-score at follow-up in children, by age at exposure. The plot shows that results in children ages 2 up to 19 years do not significantly differ from those in children up to 24 months. However, only one study included children younger than 24 months. The 95% CI for the subgroup in children ages 2 up to 19 years included 0.

Figure A 41 Meta-analysis of SSB at baseline (continuous, 8 oz/d) and BMI z-score at follow-up in children, by sex*

* BMI z-score: body mass index z-score; CI: confidence interval; d: day; ML: multilevel; mo: month; oz: ounce; PI: prediction interval; SSB: sugar-sweetened beverage; y: year; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of SSB at baseline (measured continuously, per 8 oz/d intake) and change in BMI z-score in children, by sex. The plot shows that results in only females or only in males do not significantly differ from those in mixed samples. In all three subgroups, but the 95% CI crosses 0.

Figure A 42 Meta-analysis of SSB at baseline (continuous, 8 oz/d) and BMI z-score at follow-up in children, by TEI*

* Adj: adjusted; BMI z-score: body mass index z-score; CI: confidence interval; d: day; ML: multilevel; mo: month; oz: ounce; PI: prediction interval; SSB: sugar-sweetened beverage; TEI: total energy intake; y: year; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of SSB at baseline (measured continuously, per 8 oz/d intake) and BMI z-score at follow-up in children, by TEI adjustment. The plot shows that results adjusting for TEI do not significantly differ from those that do not adjust for TEI. In both subgroups, the 95% CI crosses 0.

Figure A 43 Meta-analysis of SSB at baseline (continuous, 8 oz/d) and BMI z-score at follow-up in children, by baseline weight status*

* BMI z-score: body mass index z-score; CI: confidence interval; d: day; ML: multilevel; mo: month; OWO: overweight and/or obesity; oz: ounce; RE: random effects; PI: prediction interval; SSB: sugar-sweetened beverage; y: year; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of SSB at baseline (measured continuously, per 8 oz/d intake) and BMI z-score at follow-up in children, by baseline weight status. The plot shows that results for participants without OWO do not significantly differ from those with any weight status. In both subgroups, the 95% CI crosses 0.

Figure A 44 Meta-analysis of SSB at baseline (continuous, 8 oz/d) and BMI z-score at follow-up in children, by juice content*

* BMI z-score: body mass index z-score; CI: confidence interval; d: day; ML: multilevel; mo: month; oz: ounce; PI: prediction interval; SSB: sugar-sweetened beverage; y: year; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of SSB at baseline (measured continuously, per 8 oz/d intake) and change in BMI z-score in children, by juice content. The plot shows that results that include juice in the SSB measure do not significantly differ from those that do not report including juice. In both subgroups the 95% CI crosses zero.

Figure A 45 Meta-analysis of SSB at baseline (continuous, 8 oz/d) and BMI z-score at follow-up during childhood or adulthood, by age at outcome*

* BMI z-score; body mass index z-score; BMI z-score: body mass index z-score; CI: confidence interval; d: day; ML: multilevel; mo: month; oz: ounce; PI: prediction interval; SSB: sugar-sweetened beverage; y: year; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of SSB at baseline (measured continuously, per 8 oz/d intake) and change in BMI z-score in children, by age at outcome. All results for outcomes measured in adulthood were from the same study (Nissinen), so a subgroup analysis was not conducted.

Figure A 46 Meta-analysis of SSB at baseline (continuous, 8 oz/d) and BMI z-score at follow-up in children, by duration between exposure and outcome assessment*

* BMI z-score: body mass index z-score; CI: confidence interval; d: day; f/u: follow-up; ML: multilevel; mo: month; oz: ounce; PI: prediction interval; SSB: sugar-sweetened beverage; y: year; vertical dotted line shows null effect

This figure shows a forest plot that demonstrates that the duration between exposure and outcome assessment is not associated with the relationship between SSB at baseline (measured continuously, per 8 oz/d intake) and change in BMI z-score in children.

#### Any SSB intake versus rare or no intake

The main analysis (https://gbc-word-edit.officeapps.live.com/we/wordeditorframe.aspx?ui=en-US&rs=en-US&wopisrc=https%3A%2F%2Fnih.sharepoint.com%2Fsites%2FORS-ORF-2025DGACTeam%2F_vti_bin%2Fwopi.ashx%2Ffiles%2F63aedf44ca2d4be7b6d63d9cd322b670&wdenableroaming=1&mscc=1&hid=689245A1-4006-6000-1CBE-F25EFC5FD754.0&uih=sharepointcom&wdlcid=en-US&jsapi=1&jsapiver=v2&corrid=f0463334-69dd-6ea8-23b9-a008d9620370&usid=f0463334-69dd-6ea8-23b9-a008d9620370&newsession=1&sftc=1&uihit=docaspx&muv=1&cac=1&sams=1&mtf=1&sfp=1&sdp=1&hch=1&hwfh=1&dchat=1&sc=%7B%22pmo%22%3A%22https%3A%2F%2Fnih.sharepoint.com%22%2C%22pmshare%22%3Atrue%7D&ctp=LeastProtected&rct=Normal&wdorigin=AuthPrompt.Sharing.DirectLink.Copy&instantedit=1&wopicomplete=1&wdredirectionreason=Unified_SingleFlush#_Meta-analysis) examining the change in SSB intake (increase in intake versus no change or decrease in intake) and change in BMI in children is reported above (Table 5) and in Figure A 47. Additionally, there was sufficient evidence to examine the relationship with effects reported separately for individual racial and/or ethnic groups (Figure A 48). Subgroup analyses and meta-regressions are presented in Table A 12.

A statistically significant difference was seen between age subgroups, but only one study included children older than 24 months. Weight status at baseline may moderate the relationship, but a single study included only children without overweight or obesity at baseline. No statistically significant subgroup differences were found by TEI adjustment or whether juice was included in the SSB exposure.

Figure A 47 Meta-analysis of SSB at baseline (categorical, any versus rare or no intake) and BMI z-score at follow-up in children*

* BMI z-score: body mass index z-score; CI: confidence interval; d: day; ML: multilevel; mo: month; oz: ounce; PI: prediction interval; SSB: sugar-sweetened beverage; wk: week; vs: versus; y: year; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of SSB at baseline (measured categorically as any SSB intake versus rare or no intake) and BMI z-score at follow-up in children. Overall, BMI z-score at follow-up is 0.09 (95% CI: 0.05, 0.12) greater with any SSB intake.

Figure A 48 Meta-analysis of SSB at baseline (categorical, any versus rare or no intake) and BMI z-score at follow-up in children, with racial and/or ethnic groups reported separately*

* BMI z-score: body mass index z-score; CI: confidence interval; d: day; ML: multilevel; mo: month; oz: ounce; PI: prediction interval; SSB: sugar-sweetened beverage; wk: week; vs: versus; y: year; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of SSB at baseline (measured categorically as any SSB intake versus rare or no intake) and BMI z-score at follow-up in children, with racial and/or ethnic groups reported separately. Overall, BMI z-score at follow-up is 0.10 (95% CI: 0.05, 0.15) greater with any SSB intake.

Table A 21 Summary of subgroup analyses for SSB at baseline (categorical, any versus rare or no intake) and BMI z-score at follow-up in children^*^ * β: slope; BMI: body mass index; CI: confidence interval; mo: month; NA: not applicable; NR: not reported; OWO: overweight and/or obesity; ref: reference; SSB: sugar-sweetened beverage(s); TEI: total energy intake; vs: versus; y: year

Subgroup Analysis; Comparison | Test of Subgroup Differences; β (95% CI), p-value | Model Summary of Subgroup 1; β (95% CI), p-value | Model Summary of Subgroup 2; β (95% CI), p-value | Model Summary of Subgroup 3; β (95% CI), p-value
Age at Exposure; 2 up to 19y vs Birth up to 24mo (ref) | −0.02 (−0.09, 0.05), p=0.58 | [underlined: Up to 24mo]; 0.10 (0.04, 0.16), p<0.01 | [underlined: 2 up to 19y]; NR (All data points from single study) | NA
Sex; Females vs All (ref); Males vs All (ref) | NA; (Only “All” included) | NA | NA | NA
TEI; TEI adjusted vs Unadjusted (ref) | 0.03 (−0.05, 0.10), p=0.46 | [underlined: TEI unadjusted]; 0.03 (−0.05, 0.10), p=0.46 | [underlined: TEI adjusted]; 0.09 (−0.01, 0.19), p=0.09 | NA
Baseline Weight Status; Without OWO vs Any (ref) | 0.04 (−0.04, 0.28), p=0.28 | [underlined: Any]; 0.08 (0.04, 0.12), p<0.01 | [underlined: Without OWO]; NR (All data points from single study) | NA
Juice in SSB measure; Includes juice vs No juice reported (ref) | 0.03 (−0.05, 0.10), p=0.49 | [underlined: No juice reported]; 0.08 (0.04, 0.12), p<0.01 | [underlined: Includes juice]; 0.10 (0.01, 0.19), p=0.03 | NA
Duration of follow-up; NA (time between baseline and follow-up modeled continuously) | 0.01 (−0.01, 0.04), p=0.39 | NA | NA | NA

#### Some SSB intake versus less intake

Meta-analyses for SSB intake at baseline, measured categorically as some SSB intake versus less intake, and BMI z-score at follow-up in children were conducted: main analysis (Figure A 49), and subgroup analyses by age at exposure, by total energy intake, by juice content, by sex, and by baseline weight status (Table A 13). Additionally, there was sufficient evidence to examine the relationship with effects reported separately for individual racial and/or ethnic groups (Figure A 50). Age at outcome was also examined (Figure A 51).

A statistically significant, detrimental relationship occurred in studies examining some intake versus less intake and BMI in adulthood. No other subgroup analyses revealed statistically significant moderators, although it was not possible to conduct a subgroup analysis by baseline weight status due to lack of variation.

Figure A 49 Meta-analysis of SSB at baseline (categorical, some versus less intake) and BMI z-score at follow-up in children*

* BMI z-score: body mass index z-score; CI: confidence interval; d: day; g: gram; ML: multilevel; mo: month; oz: ounce; PI: prediction interval; SSB: sugar-sweetened beverage; svg: serving; wk: week; vs: versus; y: year; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of SSB at baseline (measured categorically as some SSB intake versus less intake) and BMI z-score at follow-up in children. Overall, there was not a statistically significant difference in the BMI z-score at follow-up among children with some SSB intake: 0.04 (95% CI: −0.00, 0.09).

Figure A 50 Meta-analysis of SSB at baseline (categorical, some versus less intake) and BMI z-score at follow-up in children, with racial and/or ethnic groups reported separately*

* BMI z-score: body mass index z-score; CI: confidence interval; d: day; g: gram; ML: multilevel; mo: month; oz: ounce; PI: prediction interval; SSB: sugar-sweetened beverage; svg: serving; wk: week; vs: versus; y: year; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of SSB at baseline (measured categorically as some SSB intake versus less intake) and BMI z-score at follow-up in children, with racial and/or ethnic groups reported separately. Overall, BMI z-score at follow-up is not significantly associated with SSB intake: 0.04 (95% CI: −0.00, 0.09).

Table A 22 Summary of subgroup analyses for SSB at baseline (categorical, some versus less intake) and BMI z-score at follow-up in children^*^ * β: slope; BMI: body mass index; CI: confidence interval; mo: month; NA: not applicable; NR: not reported; OWO: overweight and/or obesity; ref: reference; SSB: sugar-sweetened beverage(s); TEI: total energy intake; vs: versus; y: year

Subgroup Analysis; Comparison | Test of Subgroup Differences; β (95% CI), p-value | Model Summary of Subgroup 1; β (95% CI), p-value | Model Summary of Subgroup 2; β (95% CI), p-value | Model Summary of Subgroup 3; β (95% CI), p-value
Age at Exposure; 2 up to 19y vs Birth up to 24mo (ref) | 0.05 (−0.09, 0.19), p=0.48 | [underlined: Up to 24mo]; 0.04 (−0.00, 0.07), p=0.07 | [underlined: 2 up to 19y]; 0.10 (−0.06, 0.25), p=0.22 | NA
Sex; Females vs All (ref); Males vs All (ref) | 0.02 (−0.13, 0.17), p=0.78; −0.05 (−0.21, 0.11), p=0.51 | [underlined: All]; 0.06 (−0.04, 0.16), p=0.25 | [underlined: Females]; 0.07 (0.01, 0.13), p=0.02 | [underlined: Males]; NR (All data points from single study)
TEI; TEI adjusted vs Unadjusted (ref) | 0.02 (−0.12, 0.16), p=0.79 | [underlined: TEI unadjusted]; 0.07 (−0.08, 0.22), p=0.33 | [underlined: TEI adjusted]; 0.08 (−0.00, 0.16), p=0.06 | NA
Baseline Weight Status; Without OWO vs Any (ref) | NA; (Only “Any” or “Unclear” included) | NA | NA | NA
Juice in SSB measure; Includes juice vs No juice reported (ref) | 0.16 (0.04, 0.29), p=0.01 | [underlined: No juice reported]; 0.02 (−0.02, 0.06), p=0.29 | [underlined: Includes juice]; 0.18 (0.04, 0.32), p=0.01 | NA
Duration of follow-up; NA (time between baseline and follow-up modeled continuously) | −0.002 (−0.02, 0.02), p=0.80 | NA | NA | NA

Figure A 51 Meta-analysis of SSB at baseline (categorical, some versus less intake) and BMI z-score at follow-up in children, by age at outcome*

* BMI z-score: body mass index z-score; CI: confidence interval; d: day; g: gram; ML: multilevel; mo: month; oz: ounce; PI: prediction interval; SSB: sugar-sweetened beverage; svg: serving; wk: week; vs: versus; y: year; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of SSB at baseline (measured categorically as some SSB intake versus less intake) and BMI z-score at follow-up in childhood and BMI at follow-up in adulthood. While there was not a statistically significant difference in the BMI z-score in childhood, individuals who consumed some SSB in childhood had higher BMI scores in adulthood: 0.14 (0.08, 0.19).

The contoured funnel plot of the meta-analysis of SSB at baseline (measured categorically, some SSB intake versus less SSB intake) and BMI z-score at follow-up in children is presented in Figure A 52. The trim and fill method suggests 3 missing studies (1 significant) at the left, indicating potential publication bias. Egger’s test showed no significant asymmetry (p=0.16), suggesting a lack of non-reporting bias or asymmetry in this relatively homogeneous data.

Figure A 52 Contoured funnel plot of slopes for SSB at baseline (categorical, some versus less intake) and BMI z-score at follow-up in children *

* BMI z-score: body mass index z-score; SSB: sugar-sweetened beverage

This figure shows a contoured funnel plot summarizing the meta-analysis of SSB at baseline (measured categorically as some SSB intake versus less intake) and BMI z-score at follow-up in children. The plot shows 3 imputed studies with small standard errors and negative effect sizes. Two studies had a p-value >0.10 and the other had p=0.05.

### SSB intake at baseline and percent body fat at follow-up in children

#### Continuous SSB intake

In addition to the main analysis (Figure A 53), the following subgroup analyses were conducted for SSB at baseline and percent body fat at follow-up in children were conducted: by sex (Figure A 54), by total energy intake (Figure A 55), by juice content (Figure A 56), and by timing of outcome (Figure A 57). Subgroup analyses by age at exposure and by baseline weight status were not possible due to lack of variation in the evidence. The meta-regression of duration between exposure and outcome assessment is shown in Figure A 58. None of the completed subgroup analyses revealed statistically significant moderators.

Figure A 53 Meta-analysis of SSB at baseline (continuous, 8 oz/d) and percent body fat at follow-up in children*

* CI: confidence interval; d: day; ML: multilevel; oz: ounce; PI: prediction interval; SSB: sugar-sweetened beverage; y: year; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of SSB at baseline (measured continuously, per 8 oz/d intake) and percent body fat at follow-up in children. Overall, percent body fat at follow-up is 1.18 (95% CI: 0.22, 2.14) greater with each additional 8 oz/d SSB.

Figure A 54 Meta-analysis of SSB at baseline (continuous, 8 oz/d) and percent body fat at follow-up in children, by sex*

* CI: confidence interval; d: day; ML: multilevel; oz: ounce; PI: prediction interval; SSB: sugar-sweetened beverage; y: year; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of SSB at baseline (measured continuously, per 8 oz/d intake) and percent body fat at follow-up in children, by sex. The plot shows that results among only males or only female do not significantly differ from those in mixed samples. In mixed samples, there is an increase in percent body fat in children with each additional increase of 8 oz/d SSB. When males and females are assessed separately, the 95% CI crosses 0.

Figure A 55 Meta-analysis of SSB at baseline (continuous, 8 oz/d) and percent body fat at follow-up in children, by TEI*

* Adj: adjusted; CI: confidence interval; d: day; ML: multilevel; oz: ounce; PI: prediction interval; SSB: sugar-sweetened beverage; TEI: total energy intake; y: year; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of SSB at baseline (measured continuously, per 8 oz/d intake) and percent body fat at follow-up in children, by TEI adjustment. The plot shows that results adjusting for TEI do not significantly differ from those that do not adjust for TEI. In TEI unadjusted results, there is an increase in percent body fat in children with each additional increase of 8 oz/d SSB. The TEI adjusted results trend in the same direction, but the 95% CI crosses 0.

Figure A 56 Meta-analysis of SSB at baseline (continuous, 8 oz/d) and percent body fat at follow-up in children, by juice content*

* CI: confidence interval; d: day; ML: multilevel; oz: ounce; PI: prediction interval; SSB: sugar-sweetened beverage; y: year; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of SSB at baseline (measured continuously, per 8 oz/d intake) and percent body fat at follow-up in children, by juice content. The plot shows that results including fruit juice do not significantly differ from those that do not report including fruit juice. When juiced is included, there is an increase in percent body fat in children with each additional increase of 8 oz/d SSB. When juice is not reported the results trend in the same direction, but the 95% CI crosses 0.

Figure A 57 Meta-analysis of SSB at baseline (continuous, 8 oz/d) and percent body fat at follow-up in children, by age at outcome*

* CI: confidence interval; d: day; ML: multilevel; oz: ounce; PI: prediction interval; SSB: sugar-sweetened beverage; y: year; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of SSB at baseline (measured continuously, per 8 oz/d intake) and percent body fat at follow-up in childhood and in adulthood. All results for outcomes measured in adulthood were from the same study (Stoof), so a subgroup analysis was not conducted.

Figure A 58 Meta-analysis of SSB at baseline (continuous, 8 oz/d) and percent body fat at follow-up in children, by duration between exposure and outcome assessment*

* CI: confidence interval; d: day; f/u: follow-up; ML: multilevel; oz: ounce; PI: prediction interval; SSB: sugar-sweetened beverage; y: year; vertical dotted line shows null effect

This figure shows a forest plot that demonstrates that the duration between exposure and outcome assessment is not associated with the relationship between SSB at baseline (measured continuously, per 8 oz/d intake) and percent body fat in children.

## SSB-Adults

Table A 23 Data transformations and assumptions for meta-analyses in adults^*^ * Abbreviations: ASB: artificially sweetened beverage; β: regression coefficient; BL: baseline; BMI: body mass index; CI: confidence interval; d: day; fl oz: fluid ounces; g: gram; kcal: kilocalorie; ln: natural log; mL: milliliter; mo: month; n=sample size; NR: not reported; OR: odds ratio; oz: ounce; Q#: quartile; SE: standard error; SMD: standardized mean difference; svg: serving; TEI: total energy intake; USB: unswetened beverage; vs: versus; wk: week; y: year

Reference Observation | Extracted Data | Transformations and assumptions | Transformed Effect Estimate
Auerbach, 2018, TEI unadjusted | 3y change in weight per 6 oz serving change in SSBs; β (95% CI); 0.58 (0.26, 0.9) | Converted 95% CI to SE.; Coefficients were converted to 12 oz svg/d by multiplying values by 2. | β (SE); 1.16 (0.33)
Auerbach, 2018; TEI adjusted | 3y change in weight per 6 oz serving change in SSBs; β (95% CI); 0.36 (0.29, 0.69) | Converted 95% CI to SE.; Coefficients were converted to 12 oz svg/d by multiplying values by 2. | β (SE); 0.72 (0.20)
Barrio-Lopez, 2013; Abdominal obesity | 6y odds of abdominal obesity for high vs. low SSB consumption; OR (95% CI); 1.18 (1.01, 1.37) | Converted OR to ln(OR) and 95% CI to SE of ln(OR) for analysis. Back-transformed OR is presented in forest plot. | ln(OR) (SE); 0.17 (0.08)
Barrio-Lopez, 2013; Change in Weight; Q2 vs Q1 | 6y change in weight for a −28.58 to <0 mL/d change in SSB consumption vs. a <-28.57 mL/d change; β (95% CI); 0.5 (0.2, 0.9) | Converted 95% CI to SE. | β (SE); 0.50 (0.18)
Barrio-Lopez, 2013; Change in Weight; Q3 vs Q1 | 6y change in weight for a 0 mL/d change in SSB consumption vs. a <-28.57 mL/d change; β (95% CI); 0.5 (0.2, 0.8) | Converted 95% CI to SE. | β (SE); 0.50 (0.15)
Barrio-Lopez, 2013; Change in Weight; Q4 vs Q1 | 6y change in weight for a >0 to 33.81 mL/d change in SSB consumption vs. a <-28.57 mL/d change; β (95% CI); 1.1 (0.8, 1.4) | Converted 95% CI to SE. | β (SE); 1.10 (0.15)
Barrio-Lopez, 2013; Change in Weight; Q5 vs Q1 | 6y change in weight for a >33.81 mL/d change in SSB consumption vs. a <-28.57 mL/d change; β (95% CI); 1.3 (1.1, 1.6) | Converted 95% CI to SE. | β (SE); 1.30 (0.13)
Bes-Rastrollo, 2006; Q4 vs. Q1 | 2.4y change in weight for 33.4–87.4 mL/d vs. <5.5 mL/d sugar- sweetened soft drinks; β (95% CI); 1.00 (0.4, 1.6) | Converted 95% CI to SE. | β (SE); 1.00 (0.31)
Bes-Rastrollo, 2006, Q5 vs. Q1 | 2.4y change in weight for ≥87.5 mL/d vs. <5.5 mL/d sugar- sweetened soft drinks; β (95% CI); 1.2 (0.6, 1.8) | Converted 95% CI to SE. | β (SE); 1.20 (0.31)
Buso, 2022; Change in Weight; Continuous Intake; TEI unadjusted | 4y change in weight per 150 mL serving SSBs; β (SE); 0.02 (0.01) | Coefficients were converted to 12 oz svg/d by multiplying estimates by 2.367. | β (SE); 0.05 (0.02)
Buso, 2022; Change in Weight; Continuous Intake; TEI adjusted | 4y change in weight per 150 mL serving SSBs; β (SE); 0.02 (0.01) | Coefficients were converted to 12 oz svg/d by multiplying estimates by 2.367. | β (SE); 0.05 (0.02)
Buso, 2022; Change in Weight; Continuous Intake; Females | 4y change in weight per 150 mL serving SSBs; β (SE); 0.02 (0.01) | Coefficients were converted to 12 oz svg/d by multiplying estimates by 2.367. | β (SE); 0.05 (0.02)
Buso, 2022; Change in Weight; Continuous Intake; Males | 4y change in weight per 150 mL serving SSBs; β (SE); 0.02 (0.01) | Coefficients were converted to 12 oz svg/d by multiplying estimates by 2.367. | β (SE); 0.05 (0.02)
Buso, 2022; Change in Weight; Continuous Intake; <46y | 4y change in weight per 150 mL serving SSBs; β (SE); 0.02 (0.01) | Coefficients were converted to 12 oz svg/d by multiplying estimates by 2.367. | β (SE); 0.05 (0.02)
Buso, 2022; Change in Weight; Continuous Intake; ≥46y | 4y change in weight per 150 mL serving SSBs; β (SE); 0.01 (0.01) | Coefficients were converted to 12 oz svg/d by multiplying estimates by 2.367. | β (SE); 0.02 (0.02)
Buso, 2022; Change in Waist; Circumference; TEI unadjusted | 4y change in waist circumference per 150 mL serving SSBs; β (SE); 0.03 (0.01) | Coefficients were converted to 12 oz svg/d by multiplying estimates by 2.367. | β (SE); 0.07 (0.02)
Buso, 2022; Change in Waist; Circumference; TEI adjusted | 4y change in waist circumference per 150 mL serving SSBs; β (SE); 0.04 (0.01) | Coefficients were converted to 12 oz svg/d by multiplying estimates by 2.367. | β (SE); 0.09 (0.02)
Buso, 2022; Change in Waist; Circumference; Females | 4y change in waist circumference per 150 mL serving SSBs; β (SE); 0.04 (0.02) | Coefficients were converted to 12 oz svg/d by multiplying estimates by 2.367. | β (SE); 0.09 (0.05)
Buso, 2022; Change in Waist; Circumference; Males | 4y change in waist circumference per 150 mL serving SSBs; β (SE); 0.02 (0.01) | Coefficients were converted to 12 oz svg/d by multiplying estimates by 2.367. | β (SE); 0.05 (0.02)
Buso, 2022; Change in Waist; Circumference; <46y | 4y change in waist circumference per 150 mL serving SSBs; β (SE); 0.04 (0.01) | Coefficients were converted to 12 oz svg/d by multiplying estimates by 2.367. | β (SE); 0.09 (0.02)
Buso, 2022; Change in Waist; Circumference; ≥46y | 4y change in waist circumference per 150 mL serving SSBs; β (SE); 0.04 (0.02) | Coefficients were converted to 12 oz svg/d by multiplying estimates by 2.367. | β (SE); 0.09 (0.05)
Campos, 2015; Change in Weight | Weight at 4wk and 16wk for artificially sweetened beverage intervention vs. control; Intervention Group Mean at 4wk (SE): 95.16 (3.8), n1=14; Control Group Mean at 4wk (SE): 90.16 (4.0), n2=13; Intervention Group Mean at 16wk (SE): 93.76 (3.7); Control Group Mean at 16wk (SE): 91.06 (3.9) | The SMD was calculated between the intervention and control groups as the difference in mean change divided by the pooled standard deviation. Variance calculated as =((n1+n2)/(n1*n2))+SMD^2^/(2(n1+n2)) | SMD (var); 0.16 (0.15)
Campos, 2015; Change in BMI | BMI at 4wk and 16wk for artificially sweetened beverage intervention vs. control; Intervention Group Mean at 4wk (SE): 31.5 (1.2), n1=14; Control Group Mean at 4wk (SE): 30.6 (1.5), n2=13; Intervention Group Mean at 16wk (SE): 31.0 (1.2); Control Group Mean at 16wk (SE): 31.0 (1.4) | The SMD was calculated between the intervention and control groups as the difference in mean change divided by the pooled standard deviation. Variance calculated as =((n1+n2)/(n1*n2))+SMD^2^/(2(n1+n2)) | SMD (var); 0.18 (0.15)
Campos, 2015; Change in Fat Mass | % fat mass at 4wk and 16wk for artificially sweetened beverage intervention vs. control; Intervention Group Mean at 4wk (SE): 35.3 (1.8), n1=14; Control Group Mean at 4wk (SE): 34.1 (2.4), n2=13; Intervention Group Mean at 16wk (SE): 34.0 (2.1); Control Group Mean at 16wk (SE): 34.8 (2.3) | The SMD was calculated between the intervention and control groups as the difference in mean change divided by the pooled standard deviation. Variance calculated as =((n1+n2)/(n1*n2))+SMD^2^/(2(n1+n2)) | SMD (var); 0.26 (0.15)
Chen, 2009; Continuous Intake; 6 mo | 0.5y change in weight per 12 oz serving change in SSBs; β (95% CI); 0.49 (0.11, 0.82) | Converted 95% CI to SE. | β (SE); 0.49 (0.18)
Chen, 2009; Continuous Intake; 18 mo | 1.5y change in weight per 12 oz serving change in SSBs; β (95% CI); 0.65 (0.22, 1.09) | Converted 95% CI to SE. | β (SE); 0.65 (0.22)
Dhingra, 2007; Obesity | Odds of obesity for ≥1 svg/d soft drinks vs. none; OR (95% CI); 1.31 (1.02, 1.68) | Converted OR to ln(OR) and 95% CI to SE of ln(OR) for analysis. Back-transformed OR is presented in forest plot. | ln(OR) (SE); 0.27 (0.13)
Dhingra, 2007; Abdominal obesity | Odds of abdominal obesity for ≥1 svg/d soft drinks vs. none; OR (95% CI); 1.30 (1.09, 1.56) | Converted OR to ln(OR) and 95% CI to SE of ln(OR) for analysis. Back-transformed OR is presented in forest plot. | ln(OR) (SE); 0.26 (0.09)
Ebbeling, 2020; Change in Fat Mass; ASB | 1y adjusted change in fat mass for sugar-sweetened beverage intervention vs. artificially sweetened beverage control; SSB Mean: 1, n1=44; ASB Mean: 0.1, n1=44 | The SMD was calculated between the intervention and control groups as the difference in adjusted mean change divided by the pooled standard deviation. Variance calculated as =((n1+n2)/(n1*n2))+SMD^2^/(2(n1+n2)) | SMD (var); −0.10 (0.05)
Ebbeling, 2020; Change in Fat Mass; USB | 1y adjusted change in fat mass for sugar-sweetened beverage intervention vs. unsweetened beverage control; SSB Mean: 1, n1=44; USB Mean: 0.1, n1=52 | The SMD was calculated between the intervention and control groups as the difference in adjusted mean change divided by the pooled standard deviation. Variance calculated as =((n1+n2)/(n1*n2))+SMD^2^/(2(n1+n2)) | SMD (var); −0.10 (0.04)
Ebbeling, 2020; Change in Weight; SSB vs. LNCSB | 1y adjusted change in weight for sugar-sweetened beverage intervention vs. artificially sweetened beverage control; SSB Mean: 1.2, n1=60; ASB Mean: 0.6, n1=60 | The SMD was calculated between the intervention and control groups as the difference in adjusted mean change divided by the pooled standard deviation. Variance calculated as =((n1+n2)/(n1*n2))+SMD^2^/(2(n1+n2)) | SMD (var); 0.04 (0.03)
Ebbeling, 2021; Change in Weight; SSB vs. Water | 1y adjusted change in weight for sugar-sweetened beverage intervention vs. unsweetened beverage control; SSB Mean: 1.2, n1=60; USB Mean: 0.7, n1=66 | The SMD was calculated between the intervention and control groups as the difference in adjusted mean change divided by the pooled standard deviation. Variance calculated as =((n1+n2)/(n1*n2))+SMD^2^/(2(n1+n2)) | SMD (var); 0.03 (0.03)
Funtikova, 2015; Abdominal Obesity; <1 svg/d vs. None | 9y odds of abdominal obesity for <1 svg/d soft drinks vs. none; OR (95% CI); 1.22 (0.9, 1.66) | Converted OR to ln(OR) and 95% CI to SE of ln(OR) for analysis. Back-transformed OR is presented in forest plot. | ln(OR) (SE); 0.20 (0.16)
Funtikova, 2015; Abdominal Obesity; ≥1 svg/d vs. none | 9y odds of abdominal obesity for ≥1 svg/d soft drinks vs. none; OR (95% CI); 1.77 (1.07, 2.93) | Converted OR to ln(OR) and 95% CI to SE of ln(OR) for analysis. Back-transformed OR is presented in forest plot. | ln(OR) (SE); 0.57 (0.26)
Funtikova, 2015; Abdominal Obesity; <1 svg/d vs. None; Females | 9y odds of abdominal obesity for <1 svg/d soft drinks vs. none; OR (95% CI); 1.39 (0.94, 2.05) | Converted OR to ln(OR) and 95% CI to SE of ln(OR) for analysis. Back-transformed OR is presented in forest plot. | ln(OR) (SE); 0.33 (0.20)
Funtikova, 2015; Abdominal Obesity; ≥1 svg/d vs. none; Females | 9y odds of abdominal obesity for ≥1 svg/d soft drinks vs. none; OR (95% CI); 1.64 (0.74, 3.64) | Converted OR to ln(OR) and 95% CI to SE of ln(OR) for analysis. Back-transformed OR is presented in forest plot. | ln(OR) (SE); 0.49 (0.41)
Funtikova, 2015; Abdominal Obesity; <1 svg/d vs. None; Males | 9y odds of abdominal obesity for <1 svg/d soft drinks vs. none; OR (95% CI); 1.03 (0.63, 1.69) | Converted OR to ln(OR) and 95% CI to SE of ln(OR) for analysis. Back-transformed OR is presented in forest plot. | ln(OR) (SE); 0.03 (0.25)
Funtikova, 2015; Abdominal Obesity; ≥1 svg/d vs. none; Males | 9y odds of abdominal obesity for ≥1 svg/d soft drinks vs. none; OR (95% CI); 1.62 (0.83, 3.14) | Converted OR to ln(OR) and 95% CI to SE of ln(OR) for analysis. Back-transformed OR is presented in forest plot. | ln(OR) (SE); 0.48 (0.34)
Funtikova, 2015; Change in Waist; Circumference | 9y change in waist circumference per 100 kcal/d soft drinks; β (95% CI); 1.1 (0.18, 2.03) | Converted 95% CI to SE.; Coefficients were converted to 12 oz svg/d by multiplying estimates by 5.04 (USDA FDC notes that soda contains ~42 kcal/fl oz) | β (SE); 5.54 (2.38)
Funtikova, 2015; Change in Waist; Circumference; Females | 9y change in waist circumference per 100 kcal/d soft drinks; β (95% CI); 1.32 (−0.23, 2.86) | Converted 95% CI to SE.; Coefficients were converted to 12 oz svg/d by multiplying estimates by 5.04 (USDA FDC notes that soda contains ~42 kcal/fl oz) | β (SE); 6.65 (3.97)
Funtikova, 2015; Change in Waist; Circumference; Males | 9y change in waist circumference per 100 kcal/d soft drinks; β (95% CI); 0.97 (−0.14, 2.08) | Converted 95% CI to SE.; Coefficients were converted to 12 oz svg/d by multiplying estimates by 5.04 (USDA FDC notes that soda contains ~42 kcal/fl oz) | β (SE); 4.89 (2.85)
Gibbs, 2020; 6 mo | 0.5y change in weight per 12 oz/wk change in sugary beverages; β (95% CI); 0.25 (−0.52, 1.02) | Converted 95% CI to SE.; Coefficients were converted to 12 oz svg/d by multiplying values by 7. | β (SE); 1.75 (2.75)
Gibbs, 2020; 24 mo | 2y change in weight per 12 oz/wk change in sugary beverages; β (95% CI); 1.5 (0.51, 2.48) | Converted 95% CI to SE.; Coefficients were converted to 12 oz svg/d by multiplying values by 7. | β (SE); 10.50 (3.52)
Gonzalez-Morales, 2020 | 6y change in weight per 355 mL change in soft drinks; β (95% CI); 0.02 (−0.84, 0.79) | Converted 95% CI to SE. | β (SE); 0.02 (0.42)
Halkjaer, 2009; Females | 5y change in waist circumference per 60 kcal/d sugar-sweetened soft drinks; β (95% CI); 0.01 (−0.24, 0.27) | Converted 95% CI to SE.; Coefficients were converted to 12 oz svg/d by multiplying estimates by 8.39 (USDA FDC notes that soda contains ~42 kcal/fl oz) | β (SE); 0.08 (1.09)
Halkjaer, 2009; Males | 5y change in waist circumference per 60 kcal/d sugar-sweetened soft drinks; β (95% CI); −0.02 (−0.12, 0.08) | Converted 95% CI to SE.; Coefficients were converted to 12 oz svg/d by multiplying estimates by 8.39 (USDA FDC notes that soda contains ~42 kcal/fl oz) | β (SE); −0.17 (0.43)
Hernandez-Cordero, 2014; Change in BMI | BMI at BL and 9mo for beverage intervention vs. control; Intervention Group Mean at BL (SE): 42.5 (0.1), n1=120; Control Group Mean at BL (SE): 42.2 (0.1), n2=120; Intervention Group Mean at 9mo (SE): 41.6 (0.1); Control Group Mean at 9mo (SE): 41.5 (0.2) | The SMD was calculated between the intervention and control groups as the difference in adjusted mean change divided by the pooled standard deviation. Variance calculated as =((n1+n2)/(n1*n2))+SMD^2^/(2(n1+n2)) | SMD (var); 0.18 (0.02)
Hernandez-Cordero, 2014; Change in Fat Mass | Fat mass percentage at BL and 9mo for beverage intervention vs. control; Intervention Group Mean at BL (SE): 31.0 (0.1), n1=120; Control Group Mean at BL (SE): 31.0 (0.1), n2=120; Intervention Group Mean at 9mo (SE): 30.5 (0.1); Control Group Mean at 9mo (SE): 30.7 (0.1) | The SMD was calculated between the intervention and control groups as the difference in adjusted mean change divided by the pooled standard deviation. Variance calculated as =((n1+n2)/(n1*n2))+SMD^2^/(2(n1+n2)) | SMD (var); 0.18 (0.02)
Hernandez-Cordero, 2014; Change in Weight | Weight at BL and 9mo for beverage intervention vs. control; Intervention Group Mean at BL (SE): 76.9 (0.3), n1=120; Control Group Mean at BL (SE): 76.0 (0.3), n2=120; Intervention Group Mean at 9mo (SE): 75.7 (0.3); Control Group Mean at 9mo (SE): 75.3 (0.3) | The SMD was calculated between the intervention and control groups as the difference in adjusted mean change divided by the pooled standard deviation. Variance calculated as =((n1+n2)/(n1*n2))+SMD^2^/(2(n1+n2)) | SMD (var); 0.15 (0.02)
Higgins, 2019; Aspartame; Change in BMI | BMI at BL and 12wk for aspartame-sweetened Kool-Aid intervention vs. sucrose-sweetened Kool-Aid control; Aspartame Group Mean at BL (SE): 30.04 (0.54), n1=30; Sucrose Group Mean at BL (SE): 29.60 (0.48), n2=39; Aspartame Group Mean at 12wk (SE): 30.24 (0.54); Sucrose Group Mean at 12wk (SE): 30.18 (0.49) | The SMD was calculated between the intervention and control groups as the difference in adjusted mean change divided by the pooled standard deviation. Variance calculated as =((n1+n2)/(n1*n2))+SMD^2^/(2(n1+n2)) | SMD (var); 0.13 (0.06)
Higgins, 2019; Aspartame; Change in Fat Mass | Fat mass at BL and 12wk for aspartame-sweetened Kool-Aid intervention vs. sucrose-sweetened Kool-Aid control; Aspartame Group Mean at BL (SE): 31.52 (1.46), n1=30; Sucrose Group Mean at BL (SE): 32.26 (1.29), n2=39; Aspartame Group Mean at 12wk (SE): 32.01 (1.52); Sucrose Group Mean at 12wk (SE): 33.58 (1.32) | The SMD was calculated between the intervention and control groups as the difference in adjusted mean change divided by the pooled standard deviation. Variance calculated as =((n1+n2)/(n1*n2))+SMD^2^/(2(n1+n2)) | SMD (var); 0.10 (0.06)
Higgins, 2019; RebA; Change in BMI | BMI at BL and 12wk for RebA-sweetened Kool-Aid intervention vs. sucrose-sweetened Kool-Aid control; RebA Group Mean at BL (SE): 30.25 (0.56), n1=28; Sucrose Group Mean at BL (SE): 29.60 (0.48), n2=39; RebA Group Mean at 12wk (SE): 30.44 (0.56); Sucrose Group Mean at 12wk (SE): 30.18 (0.49) | The SMD was calculated between the intervention and control groups as the difference in adjusted mean change divided by the pooled standard deviation. Variance calculated as =((n1+n2)/(n1*n2))+SMD^2^/(2(n1+n2)) | SMD (var); 0.13 (0.06)
Higgins, 2019; RebA; Change in Fat Mass | Fat mass at BL and 12wk for RebA-sweetened Kool-Aid intervention vs. sucrose-sweetened Kool-Aid control; RebA Group Mean at BL (SE): 33.03 (1.52), n1=28; Sucrose Group Mean at BL (SE): 32.26 (1.29), n2=39; RebA Group Mean at 12wk (SE): 33.11 (1.52); Sucrose Group Mean at 12wk (SE): 33.58 (1.32) | The SMD was calculated between the intervention and control groups as the difference in adjusted mean change divided by the pooled standard deviation. Variance calculated as =((n1+n2)/(n1*n2))+SMD^2^/(2(n1+n2)) | SMD (var); 0.15 (0.06)
Higgins, 2019; Saccharin; Change in BMI | BMI at BL and 12wk for saccharin-sweetened Kool-Aid intervention vs. sucrose-sweetened Kool-Aid control; Saccharin Group Mean at BL (SE): 29.22 (0.55), n1=29; Sucrose Group Mean at BL (SE): 29.60 (0.48), n2=39; Saccharin Group Mean at 12wk (SE): 29.63 (0.55); Sucrose Group Mean at 12wk (SE): 30.18 (0.49) | The SMD was calculated between the intervention and control groups as the difference in adjusted mean change divided by the pooled standard deviation. Variance calculated as =((n1+n2)/(n1*n2))+SMD^2^/(2(n1+n2)) | SMD (var); 0.06 (0.06)
Higgins, 2019; Saccharin; Change in Fat Mass | Fat mass at BL and 12wk for saccharin-sweetened Kool-Aid intervention vs. sucrose-sweetened Kool-Aid control; Saccharin Group Mean at BL (SE): 31.62 (1.49), n1=29; Sucrose Group Mean at BL (SE): 32.26 (1.29), n2=39; Saccharin Group Mean at 12wk (SE): 32.08 (1.49); Sucrose Group Mean at 12wk (SE): 33.58 (1.32) | The SMD was calculated between the intervention and control groups as the difference in adjusted mean change divided by the pooled standard deviation. Variance calculated as =((n1+n2)/(n1*n2))+SMD^2^/(2(n1+n2)) | SMD (var); 0.11 (0.06)
Higgins, 2019; Sucralose; Change in BMI | BMI at BL and 12wk for sucralose-sweetened Kool-Aid intervention vs. sucrose-sweetened Kool-Aid control; Sucralose Group Mean at BL (SE): 29.44 (0.55), n1=28; Sucrose Group Mean at BL (SE): 29.60 (0.48), n2=39; Sucralose Group Mean at 12wk (SE): 29.18 (0.57); Sucrose Group Mean at 12wk (SE): 30.18 (0.49) | The SMD was calculated between the intervention and control groups as the difference in adjusted mean change divided by the pooled standard deviation. Variance calculated as =((n1+n2)/(n1*n2))+SMD^2^/(2(n1+n2)) | SMD (var); 0.28 (0.06)
Higgins, 2019; Sucralose; Change in Fat Mass | Fat mass at BL and 12wk for sucralose-sweetened Kool-Aid intervention vs. sucrose-sweetened Kool-Aid control; Sucralose Group Mean at BL (SE): 29.80 (1.52), n1=28; Sucrose Group Mean at BL (SE): 32.26 (1.29), n2=39; Sucralose Group Mean at 12wk (SE): 29.49 (1.53); Sucrose Group Mean at 12wk (SE): 33.58 (1.32) | The SMD was calculated between the intervention and control groups as the difference in adjusted mean change divided by the pooled standard deviation. Variance calculated as =((n1+n2)/(n1*n2))+SMD^2^/(2(n1+n2)) | SMD (var); 0.20 (0.06)
Higgins, 2019; Aspartame; Change in Weight | Weight at BL and 12wk for aspartame-sweetened Kool-Aid intervention vs. sucrose-sweetened Kool-Aid control; Aspartame Group Mean at BL (SE): 86.24 (0.29), n1=30; Sucrose Group Mean at BL (SE): 86.24 (0.29), n2=39; Aspartame Group Mean at 12wk (SE): 86.97 (0.35); Sucrose Group Mean at 12wk (SE): 88.09 (0.36) | The SMD was calculated between the intervention and control groups as the difference in adjusted mean change divided by the pooled standard deviation. Variance calculated as =((n1+n2)/(n1*n2))+SMD^2^/(2(n1+n2)) | SMD (var); 0.64 (0.06)
Higgins, 2019; RebA; Change in Weight | Weight at BL and 12wk for RebA-sweetened Kool-Aid intervention vs. sucrose-sweetened Kool-Aid control; RebA Group Mean at BL (SE): 86.24 (0.35), n1=28; Sucrose Group Mean at BL (SE): 86.24 (0.29), n2=39; RebA Group Mean at 12wk (SE): 86.84 (0.37); Sucrose Group Mean at 12wk (SE): 88.09 (0.36) | The SMD was calculated between the intervention and control groups as the difference in adjusted mean change divided by the pooled standard deviation. Variance calculated as =((n1+n2)/(n1*n2))+SMD^2^/(2(n1+n2)) | SMD (var); 0.72 (0.07)
Higgins, 2019; Saccharin; Change in Weight | Weight at BL and 12wk for saccharin-sweetened Kool-Aid intervention vs. sucrose-sweetened Kool-Aid control; Saccharin Group Mean at BL (SE): 86.24 (0.29), n1=29; Sucrose Group Mean at BL (SE): 86.24 (0.29), n2=39; Saccharin Group Mean at 12wk (SE): 87.43 (0.36); Sucrose Group Mean at 12wk (SE): 88.09 (0.36) | The SMD was calculated between the intervention and control groups as the difference in adjusted mean change divided by the pooled standard deviation. Variance calculated as =((n1+n2)/(n1*n2))+SMD^2^/(2(n1+n2)) | SMD (var); 0.38 (0.06)
Higgins, 2019; Sucralose; Change in Weight | Weight at BL and 12wk for sucralose-sweetened Kool-Aid intervention vs. sucrose-sweetened Kool-Aid control; Sucralose Group Mean at BL (SE): 86.25 (0.35), n1=28; Sucrose Group Mean at BL (SE): 86.24 (0.29), n2=39; Sucralose Group Mean at 12wk (SE): 85.47 (0.37); Sucrose Group Mean at 12wk (SE): 88.09 (0.36) | The SMD was calculated between the intervention and control groups as the difference in adjusted mean change divided by the pooled standard deviation. Variance calculated as =((n1+n2)/(n1*n2))+SMD^2^/(2(n1+n2)) | SMD (var); 1.51 (0.08)
Kaikkonen, 2015; Females | 6y change in weight per svg/mo sugar-sweetened soft drinks; β (SE); 0.114 (0.05) | Serving size NR, assumed to be 12 oz.; Coefficients were converted to 12 oz svg/d by multiplying estimates by 30. | β (SE); 3.42 (1.53)
Konieczna, 2019; Change in Waist; Circumference | Yearly change in waist circumference per change in svg/d soft beverages with sugar; β (95% CI); 0.08 (−0.15, 0.31) | Converted 95% CI to SE.; Serving size NR, assumed to be 12 oz. | β (SE); 0.08 (0.12)
Konieczna, 2019; Change in Waist; Circumference; Females | Yearly change in waist circumference per change in svg/d soft beverages with sugar; β (95% CI); 0.14 (−0.18, 0.46) | Converted 95% CI to SE.; Serving size NR, assumed to be 12 oz. | β (SE); 0.14 (0.16)
Konieczna, 2019; Change in Waist; Circumference; Males | Yearly change in waist circumference per change in svg/d soft beverages with sugar; β (95% CI); 0.00 (−0.32, 0.32) | Converted 95% CI to SE.; Serving size NR, assumed to be 12 oz. | β (SE); 0.00 (0.16)
Konieczna, 2019; Change in Weight | Yearly change in weight per change in svg/d soft beverages with sugar; β (95% CI); 0.07 (−0.06, 0.19) | Converted 95% CI to SE.; Serving size NR, assumed to be 12 oz. | β (SE); 0.07 (0.06)
Kvaavik, 2005; Females | 8y odds of obesity for long-term high consumers of sugar-sweetened carbonated soft drinks vs. long-term low consumers; OR (95% CI); 0.80 (0.09, 6.85) | Converted OR to ln(OR) and 95% CI to SE of ln(OR) for analysis. Back-transformed OR is presented in forest plot. | ln(OR) (SE); −0.22 (1.11)
Kvaavik, 2005; Males | 8y odds of obesity for long-term high consumers of sugar-sweetened carbonated soft drinks vs. long-term low consumers; OR (95% CI); 2.29 (0.48, 10.96) | Converted OR to ln(OR) and 95% CI to SE of ln(OR) for analysis. Back-transformed OR is presented in forest plot. | ln(OR) (SE); 0.83 (0.80)
Lim, 2021; Change in Waist; Circumference | 6y change in waist circumference per 330 mL change in soft drinks; β (95% CI); 0.7 (−0.01, 1.41) | Converted 95% CI to SE.; Coefficients were converted to 12 oz svg/d by multiplying estimates by 1.075. | β (SE); 0.75 (0.39)
Lim, 2021; Change in Weight; Continuous Intake; All participants | 6y change in weight per 330 mL change in soft drinks; β (95% CI); 0.69 (0.05, 1.33) | Converted 95% CI to SE.; Coefficients were converted to 12 oz svg/d by multiplying estimates by 1.075. | β (SE); 0.74 (0.35)
Lim, 2021; Change in Weight; Continuous Intake; China | 6y change in weight per 330 mL change in soft drinks; β (95% CI); 0.38 (−0.45, 1.21) | Converted 95% CI to SE.; Coefficients were converted to 12 oz svg/d by multiplying estimates by 1.075. | β (SE); 0.41 (0.46)
Lim, 2021; Change in Weight; Continuous Intake; India | 6y change in weight per 330 mL change in soft drinks; β (95% CI); 2.18 (1.19, 3.18) | Converted 95% CI to SE.; Coefficients were converted to 12 oz svg/d by multiplying estimates by 1.075. | β (SE); 2.34 (0.55)
Lim, 2021; Change in Weight; Continuous Intake; Malay | 6y change in weight per 330 mL change in soft drinks; β (95% CI); 0.02 (−0.67, 0.71) | Converted 95% CI to SE.; Coefficients were converted to 12 oz svg/d by multiplying estimates by 1.075. | β (SE); 0.02 (0.38)
Lim, 2021; Change in Weight Categorical Intake Moderate Increase vs. Decrease | 6y change in weight for >0.50 svg/d increase in soft drinks vs. >0.50 svg/d decrease; β (95% CI); 1.13 (−0.3, 2.55) | Converted 95% CI to SE. | β (SE); 1.13 (0.73)
Lim, 2021; Change in Weight; Categorical Intake; No Change/Small; Increase vs. Decrease | 6y change in weight for 0–0.5 svg/d increase in soft drinks vs. >0.50 svg/d decrease; β (95% CI); 0.3 (−0.8, 1.4) | Converted 95% CI to SE. | β (SE); 0.30 (0.56)
Lim, 2021; Change in Weight; Categorical Intake Small Decrease vs. Decrease | 6y change in weight for 0.01–0.50 svg/d decrease in soft drinks vs. >0.50 svg/d decrease; β (95% CI); 0.33 (−0.7, 1.37) | Converted 95% CI to SE. | β (SE); 0.33 (0.53)
Maersk, 2012; Change in Fat Mass; Diet Soda | 0.5y change in fat mass for sucrose-sweetened soft drink intervention vs. aspartame-sweetened diet cola control; Sucrose Group Mean at BL (SE): 34.0 (8.3), n1=10; Aspartame Group Mean at BL (SE): 35.1 (9.0), n2=12; Sucrose Group Mean at 6mo: 34.0*1.0314; Aspartame Group Mean at 6mo: 35.1*0.9948 | The SMD was calculated between the intervention and control groups as the difference in adjusted mean change divided by the baseline pooled standard deviation. Variance calculated as =((n1+n2)/(n1*n2))+SMD^2^/(2(n1+n2)) | SMD (var); 0.04 (0.18)
Maersk, 2012; Change in Fat Mass; Water | 0.5y change in fat mass for sucrose-sweetened soft drink intervention vs. water control; Sucrose Group Mean at BL (SE): 34.0 (8.3), n1=10; Water Group Mean at BL (SE): 37.2 (11.6), n2=13; Sucrose Group Mean at 6mo: 34.0*1.0314; Water Group Mean at 6mo: 37.2*1.049 | The SMD was calculated between the intervention and control groups as the difference in adjusted mean change divided by the baseline pooled standard deviation. Variance calculated as =((n1+n2)/(n1*n2))+SMD^2^/(2(n1+n2)) | SMD (var); −0.02 (0.18)
Maersk, 2012; Change in Weight; Diet Soda | 0.5y change in weight for sucrose-sweetened soft drink intervention vs. aspartame-sweetened diet cola control; Sucrose Group Mean at BL (SE): 97.8 (12.5), n1=10; Aspartame Group Mean at BL (SE): 92.2 (10.9), n2=12; Sucrose Group Mean at 6mo: 97.8*1.0128; Aspartame Group Mean at 6mo: 92.2*1.00114 | The SMD was calculated between the intervention and control groups as the difference in adjusted mean change divided by the baseline pooled standard deviation. Variance calculated as =((n1+n2)/(n1*n2))+SMD^2^/(2(n1+n2)) | SMD (var); 0.02 (0.18)
Maersk, 2012; Change in Weight; Water | 0.5y change in weight for sucrose-sweetened soft drink intervention vs. water control; Sucrose Group Mean at BL (SE): 97.8 (12.5), n1=10; Water Group Mean at BL (SE): 101.7 (22.4), n2=13; Sucrose Group Mean at 6mo: 97.8*1.0128; Water Group Mean at 6mo: 101.7*1.00576 | The SMD was calculated between the intervention and control groups as the difference in adjusted mean change divided by the baseline pooled standard deviation. Variance calculated as =((n1+n2)/(n1*n2))+SMD^2^/(2(n1+n2)) | SMD (var); 0.01 (0.18)
Moshtaghian, 2021 | 15y change in weight per 1% increase in energy from beverage sources of added sugar; β (95% CI); −0.03 (−0.14, 0.08) | Converted 95% CI to SE.; Coefficients were converted to 12 oz svg/d by multiplying estimates by 24.49 (baseline energy was 2,055 kcal and USDA FDC notes that soda contains ~42 kcal/fl oz) | β (SE); −0.69 (1.41)
Mullie, 2017; Categorical Intake; <6.8 vs 0 oz/d | 10y change in weight for <1 glass SSBs vs. never; β (95% CI); 0.16 (−1.03, 1.34) | Converted 95% CI to SE. | β (SE); 0.16 (0.60)
Mullie, 2017; Categorical Intake; 6.8–23.7 vs 0 oz/d | 10y change in weight for 1–3 glasses SSBs vs. never; β (95% CI); −0.16 (−1.33, 1.01) | Converted 95% CI to SE. | β (SE); −0.16 (0.60)
Mullie, 2017; Categorical Intake; >23.7 vs 0 oz/d | 10y change in weight for >3 glasses SSBs vs. never; β (95% CI); 4.34 (1.89, 6.79) | Converted 95% CI to SE. | β (SE); 4.34 (1.25)
Mullie, 2017; Continuous Intake | 10y change in weight per mL/d increase in SSBs; β (95% CI); 0.002 (−0.001, 0.005) | Converted 95% CI to SE.; Coefficients were converted to 12 oz svg/d by multiplying estimates by 353. | β (SE); 0.71 (0.54)
Nooyens, 2005; Change in Weight | 5y change in weight per change in glasses/d sugar-sweetened soft drinks; β (SE); 0.12 (0.06) | Serving size NR, assumed to be 12 oz | β (SE); 0.12 (0.06)
Nooyens, 2005; Change in Waist; Circumference | 5y change in waist circumference per change in glasses/d sugar-sweetened soft drinks; β (SE); 0.06 (0.08) | Serving size NR, assumed to be 12 oz | β (SE); 0.06 (0.08)
Olsen, 2016; Change in Weight; TEI Unadjusted | 1y change in weight per 200 g/d soft drinks; β (95% CI); 0.06 (−0.01, 0.12) | Converted 95% CI to SE.; Coefficients were converted to 12 oz sv/d by multiplying estimates by 1.86 (USDA FDC notes 1 fl oz svg = 31 g). | β (SE); 0.11 (0.06)
Olsen, 2016; Change in Weight; TEI Adjusted | 1y change in weight per 200 g/d soft drinks; β (95% CI); 0.07 (0.01, 0.13) | Converted 95% CI to SE.; Coefficients were converted to 12 oz sv/d by multiplying estimates by 1.86 (USDA FDC notes 1 fl oz svg = 31 g). | β (SE); 0.13 (0.06)
Olsen, 2016; Change in Waist; Circumference; DCH, Inter99; TEI Unadjusted | 1y change in waist circumference per 200 g/d soft drinks; β (95% CI); 0.00 (−0.08, 0.09) | Converted 95% CI to SE.; Coefficients were converted to 12 oz sv/d by multiplying estimates by 1.86 (USDA FDC notes 1 fl oz svg = 31 g). | β (SE); 0.00 (0.08)
Olsen, 2016; Change in Waist; Circumference; DCH, Inter99; TEI Adjusted | 1y change in waist circumference per 200 g/d soft drinks; β (95% CI); 0.01 (−0.07, 0.10) | Converted 95% CI to SE.; Coefficients were converted to 12 oz sv/d by multiplying estimates by 1.86 (USDA FDC notes 1 fl oz svg = 31 g). | β (SE); 0.02 (0.08)
Pan, 2013; NHS, NHS II, HPS | 4y change in weight per change in one standard serving of SSBs; β (95% CI); 0.36 (0.24, 0.48) | Converted 95% CI to SE.; Serving size assumed to be 12 oz. | β (SE); 0.36 (0.06)
Pan, 2013; NHS, NHS II, HPS; ≤50y | 4y change in weight per change in one standard serving of SSBs; β (95% CI); 0.43 (0.35, 0.50) | Converted 95% CI to SE.; Serving size assumed to be 12 oz. | β (SE); 0.43 (0.04)
Pan, 2013; NHS, NHS II, HPS; >50y | 4y change in weight per change in one standard serving of SSBs; β (95% CI); 0.32 (0.21, 0.44) | Converted 95% CI to SE.; Serving size assumed to be 12 oz. | β (SE); 0.32 (0.06)
Pan, 2013; NHS; Females | 4y change in weight per change in one standard serving of SSBs; β (95% CI); 0.36 (0.30, 0.41) | Converted 95% CI to SE.; Serving size assumed to be 12 oz. | β (SE); 0.36 (0.03)
Pan, 2013; NHS II; Females | 4y change in weight per change in one standard serving of SSBs; β (95% CI); 0.47 (0.42, 0.52) | Converted 95% CI to SE.; Serving size assumed to be 12 oz. | β (SE); 0.47 (0.03)
Pan, 2013; HPS; Males | 4y change in weight per change in one standard serving of SSBs; β (95% CI); 0.25 (0.19, 0.31) | Converted 95% CI to SE.; Serving size assumed to be 12 oz. | β (SE); 0.25 (0.03)
Partridge, 2016; 3 mo | 0.25y change in weight per 1 L/wk decrease in SSBs; β (SE); −0.5 (0.27) | Effect estimate was multiplied by −1 to reflect a higher vs. lower intake comparison.; Coefficients were converted to 12 oz svg/d by multiplying estimates by 2.48. | β (SE); 1.24 (0.67)
Partridge, 2016; 9 mo | 0.75y change in weight per 1 L/wk decrease in SSBs; β (SE); −0.61 (0.26) | Effect estimate was multiplied by −1 to reflect a higher vs. lower intake comparison.; Coefficients were converted to 12 oz svg/d by multiplying estimates by 2.48. | β (SE); 1.51 (0.64)
Romaguera, 2011; All participants | 5.5y change in waist circumference per 100 kcal soft drinks; β (95% CI); 0.04 (0.02, 0.07) | Converted 95% CI to SE.; Coefficients were converted to 12 oz svg/d by multiplying estimates by 5.04 (USDA FDC notes that soda contains ~42 kcal/fl oz) | β (SE); 0.20 (0.06)
Romaguera, 2011; Females | 5.5y change in waist circumference per 100 kcal soft drinks; β (95% CI); 0.02 (0.00, 0.04) | Converted 95% CI to SE.; Coefficients were converted to 12 oz svg/d by multiplying estimates by 5.04 (USDA FDC notes that soda contains ~42 kcal/fl oz) | β (SE); 0.25 (0.09)
Romaguera, 2011; Males | 5.5y change in waist circumference per 100 kcal soft drinks; β (95% CI); 0.05 (0.02, 0.09) | Converted 95% CI to SE.; Coefficients were converted to 12 oz svg/d by multiplying estimates by 5.04 (USDA FDC notes that soda contains ~42 kcal/fl oz) | β (SE); 0.10 (0.05)
Smith, 2015; NHS, NHS II, HPS | 4y change in weight per 1 glass, bottle, or can of cola; β (95% CI); 0.01 (−0.08, 0.11) | Converted 95% CI to SE.; Serving size assumed to be 12 oz. | β (SE); 0.01 (0.05)
Smith, 2015; NHS; Females | 4y change in weight per 1 glass, bottle, or can of cola; β (95% CI); −0.07 (−0.18, 0.04) | Converted 95% CI to SE.; Serving size assumed to be 12 oz. | β (SE); −0.07 (0.06)
Smith, 2015; NHS II; Females | 4y change in weight per 1 glass, bottle, or can of cola; β (95% CI); −0.01 (−0.09, 0.08) | Converted 95% CI to SE.; Serving size assumed to be 12 oz. | β (SE); −0.01 (0.04)
Smith, 2015; HPS; Males | 4y change in weight per 1 glass, bottle, or can of cola; β (95% CI); 0.11 (−0.02, 0.24) | Converted 95% CI to SE.; Serving size assumed to be 12 oz. | β (SE); 0.11 (0.07)
Stern, 2017; Change in Waist; Circumference; All participants | 2y change in waist circumference per change in sugar-sweetened soda consumption; β (95% CI); 0.9 (0.5, 1.4) | Converted 95% CI to SE.; Serving size NR, assumed to be 12 oz. | β (SE); 0.9 (0.23)
Stern, 2017; Change in Waist; Circumference; <43y | 2y change in waist circumference per change in sugar-sweetened soda consumption; β (95% CI); 0.9 (0.2, 1.5) | Converted 95% CI to SE.; Serving size NR, assumed to be 12 oz. | β (SE); 0.9 (0.33)
Stern, 2017; Change in Waist; Circumference; ≥43y | 2y change in waist circumference per change in sugar-sweetened soda consumption; β (95% CI); 1.0 (0.4, 1.7) | Converted 95% CI to SE.; Serving size NR, assumed to be 12 oz. | β (SE); 1.00 (0.33)
Stern, 2017; Change in Weight; Continuous Intake; All participants | 2y change in weight per change in sugar-sweetened soda consumption; β (95% CI); 1.0 (0.7, 1.2) | Converted 95% CI to SE.; Serving size NR, assumed to be 12 oz. | β (SE); 1.00 (0.13)
Stern, 2017; Continuous Intake; Change in Weight; <43y | 2y change in weight per change in sugar-sweetened soda consumption; β (95% CI); 0.8 (0.4, 1.1) | Converted 95% CI to SE.; Serving size NR, assumed to be 12 oz. | β (SE); 0.80 (0.18)
Stern, 2017; Continuous Intake; Change in Weight; ≥43y | 2y change in weight per change in sugar-sweetened soda consumption; β (95% CI); 1.20 (0.8, 1.5) | Converted 95% CI to SE.; Serving size NR, assumed to be 12 oz. | β (SE); 1.20 (0.18)
Stern, 2017; Categorical Intake; Change in Weight | 2y change in weight for decreased <-1 svg/wk sugar-sweetened soda vs. no change; β (95% CI); −0.4 (−0.6, −0.2) | Converted 95% CI to SE.; Effect estimate was multiplied by −1 to reflect a higher vs. lower intake comparison. | β (SE); 0.4 (0.10)
Tate, 2012; SSB vs. Water | Weight at BL and 6mo for water intervention vs. “attention control” comparator; Intervention Group Mean at BL (95% CI): 98.4 (95.2, 101.6), n1=108; Control Group Mean at BL (SE): 102.6 (99.1, 106.1), n2=105; Intervention Group Mean at 6mo (95% CI): 96.5 (93.3, 99.7); Control Group Mean at 6mo (95% CI): 100.7 (97.2, 104.2) | The SMD was calculated between the intervention and control groups as the difference in mean change divided by the pooled standard deviation. Variance calculated as =((n1+n2)/(n1*n2))+SMD^2^/(2(n1+n2)) | SMD (var); 0.0 (0.02)
Tate, 2012; SSB vs. LNCSB | Weight at BL and 6mo for diet beverage intervention vs. “attention control” comparator; Intervention Group Mean at BL (95% CI): 100.9 (97.1, 104.7), n1=105; Control Group Mean at BL (SE): 102.6 (99.1, 106.1), n2=105; Intervention Group Mean at 6mo (95% CI): 98.3 (94.5, 102.1); Control Group Mean at 6mo (95% CI): 100.7 (97.2, 104.2) | The SMD was calculated between the intervention and control groups as the difference in mean change divided by the pooled standard deviation. Variance calculated as =((n1+n2)/(n1*n2))+SMD^2^/(2(n1+n2)) | SMD (var); 0.04 (0.02)
Torquati, 2021; Less sedentary job; 1–3 vs. <1 svg/wk | 3y odds of obesity for 1–3 svg/wk SSBs vs. <1 svg/wk; OR (95% CI); 1.68 (1.07, 2.67) | Converted OR to ln(OR) and 95% CI to SE of ln(OR) for analysis. Back-transformed OR is presented in forest plot. | ln(OR) (SE); 0.52 (0.23)
Torquati, 2021; Less sedentary job; >3 vs. <1 svg/wk | 3y odds of obesity for >3 svg/wk SSBs vs. <1 svg/wk; OR (95% CI); 2.08 (1.42, 3.05) | Converted OR to ln(OR) and 95% CI to SE of ln(OR) for analysis. Back-transformed OR is presented in forest plot. | ln(OR) (SE); 0.73 (0.20)
Torquati, 2021; Sedentary job; 1–3 vs. <1 svg/wk | 3y odds of obesity for 1–3 svg/wk SSBs vs. <1 svg/wk; OR (95% CI); 1.23 (0.74, 2.05) | Converted OR to ln(OR) and 95% CI to SE of ln(OR) for analysis. Back-transformed OR is presented in forest plot. | ln(OR) (SE); 0.21 (0.26)
Torquati, 2021; Sedentary job; >3 vs. <1 svg/wk | 3y odds of obesity for >3 svg/wk SSBs vs. <1 svg/wk; OR (95% CI); 1.43 (0.94, 2.21) | Converted OR to ln(OR) and 95% CI to SE of ln(OR) for analysis. Back-transformed OR is presented in forest plot. | ln(OR) (SE); 0.36 (0.22)
Tucker, 2015; vs. ASB | 4y change in weight for SSB consumption vs. ASB consumption; MD (SE); 2.69 (1.05) | None | β (SE); 2.69 (1.05)
Tucker, 2015; vs. No SSB | 4y change in weight for SSB consumption vs. no SSB consumption; MD (SE); 2.15 (0.99) | None | β (SE); 2.15 (0.99)
Vazquez-Duran, 2016; ASB | 0.5y percent change in BMI for ASB intervention (including plain water) vs. SSB usual intake control; ASB Group Mean at BL (SE): 25.48 (0.62), n1=50; SSB Group Mean at BL (SE): 26.00 (0.55), n2=49; ASB Group Mean at 6mo: 25.48*1.0011; SSB Group Mean at 6mo: 26.00*1.0057 | The SMD was calculated between the intervention and control groups as the difference in mean change divided by the baseline pooled standard deviation. Variance calculated as =((n1+n2)/(n1*n2))+SMD^2^/(2(n1+n2)) | SMD (var); 0.03 (0.04)
Vazquez-Duran, 2016; Water | 0.5y percent change in BMI for water intervention vs. SSB usual intake control; Water Group Mean at BL (SE): 27.27 (0.70), n1=49; SSB Group Mean at BL (SE): 26.00 (0.55), n2=49; Water Group Mean at 6mo: 27.27*0.9666; SSB Group Mean at 6mo: 26.00*1.0057 | The SMD was calculated between the intervention and control groups as the difference in mean change divided by the baseline pooled standard deviation. Variance calculated as =((n1+n2)/(n1*n2))+SMD^2^/(2(n1+n2)) | SMD (var); 0.24 (0.04)

### Change in SSB intake and change in weight in adults

#### Continuous SSB intake

The main analysis of the association between change in SSB intake and change in weight in adults is reported above in Table 7 and Figure 4. Figure A 59 shows the results of an additional analysis examining racial and/or ethnic groups separately. The relationship between change in SSB intake and change in weight remained significant when racial groups were reported separately, but this was only in a single study.

The following subgroup analyses and meta-regressions were conducted to examine the impact of age (Figure A 60), sex (Figure A 61), TEI adjustment (Figure A 62), juice content in the SSB measure (Figure A 63), duration between exposure and outcome assessments (Figure A 64), and whether the outcome was self-reported (Figure A 65) on the relationship between change in SSB intake and change in weight in adults. There were not statistically significant moderating effects on the relationship of interest, but some subgroups showed statistically significant associations.

Figure A 59 Meta-analysis of change in SSB (continuous, 12 oz/d) and change in weight (kg) in adults, with racial and/or ethnic groups reported separately*

* CI: confidence interval; d: day; kg: kilogram; ML: multilevel; mo: month; oz: ounce; SSB: sugar-sweetened beverage; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of change in SSB (measured continuously, per 12 oz/d intake) and change in weight in adults, with racial and/or ethnic groups reported separately. Overall, weight increases by 0.54 (95% CI: 0.26, 0.81) kg in adults with each additional increase of 12 oz/d SSB.

Figure A 60 Meta-analysis of change in SSB (continuous, 12 oz/d) and change in weight (kg) in adults, by age at exposure*

* CI: confidence interval; d: day; kg: kilogram; ML: multilevel; oz: ounce; PI: prediction interval; SSB: sugar-sweetened beverage; y: year; vertical dotted line shows null effect

This figure shows a forest plot that demonstrates that age at exposure is not associated with the relationship between change in SSB (measured continuously, per 12 oz/d intake) and change in weight in adults.

Figure A 61 Meta-analysis of change in SSB (continuous, 12 oz/d) and change in weight (kg) in adults, by sex*

* CI: confidence interval; d: day; kg: kilogram; ML: multilevel; oz: ounce; PI: prediction interval; SSB: sugar-sweetened beverage; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of change in SSB (measured continuously, per 12 oz/d intake) and change in weight in adults, by sex. The plot shows that results in only females or only in males do not significantly differ from those in mixed samples. In all 3 subgroups, there is a statistically significant increase in weight in adults with each additional increase of 12 oz/d SSB.

Figure A 62 Meta-analysis of change in SSB (continuous, 12 oz/d) and change in weight (kg) in adults, by TEI*

* Adj: adjusted; CI: confidence interval; d: day; kg: kilogram; ML: multilevel; oz: ounce; PI: prediction interval; SSB: sugar-sweetened beverage; TEI: total energy intake; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of change in SSB (measured continuously, per 12 oz/d intake) and change in weight in adults, by TEI adjustment. The plot shows that TEI-adjusted results do not significantly differ from unadjusted results. In both subgroups, there is a statistically significant increase in weight in adults with each additional increase of 12 oz/d SSB.

Figure A 63 Meta-analysis of change in SSB (continuous, 12 oz/d) and change in weight (kg) in adults, by juice content*

* CI: confidence interval; d: day; kg: kilogram; ML: multilevel; mo: month; oz: ounce; PI: prediction interval; SSB: sugar-sweetened beverage; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of change in SSB (measured continuously, per 12 oz/d intake) and change in weight in adults, by juice content. The plot shows that results that include juice in the SSB measure do not significantly differ from those that do not report including juice. In both subgroups, there is a statistically significant increase in weight in adults with each additional increase of 12 oz/d SSB.

Figure A 64 Meta-analysis of change in SSB (continuous, 12 oz/d) and change in weight (kg) in adults, by duration between exposure and outcome assessment*

* CI: confidence interval; d: day; f/u: follow-up; kg: kilogram; ML: multilevel; mo: month; oz: ounce; PI: prediction interval; SSB: sugar-sweetened beverage; vertical dotted line shows null effect

This figure shows a forest plot that demonstrates that duration between exposure and outcome assessment is not associated with the relationship between change in SSB (measured continuously, per 12 oz/d intake) and change in weight in adults.

Figure A 65 Meta-analysis of change in SSB (continuous, 12 oz/d) and change in weight (kg) in adults, by self-reported outcome*

* CI: confidence interval; d: day; kg: kilogram; ML: multilevel; mo: month; oz: ounce; PI: prediction interval; SSB: sugar-sweetened beverage; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of change in SSB (measured continuously, per 12 oz/d intake) and change in weight in adults, by self-reported outcome. The plot shows that self-reported results do not significantly differ from staff-measured results. In both subgroups, there is a statistically significant increase in weight in adults with each additional increase of 12 oz/d SSB.

Egger’s test showed statistically significant asymmetry (p=0.01), which may indicate non-reporting bias or heterogeneity. The contoured funnel plot of the main analysis for change in SSB intake and change in weight is depicted in Figure A 66. The trim and fill method suggests 2 missing studies, including 1 significant study, which is consistent with potential publication bias.

Figure A 66 Contoured funnel plot of slopes for change in SSB (continuous, 12 oz/d) and change in weight (kg) in adults

This figure shows a contoured funnel plot of slopes for change in SSB intake (measured continuously, per 12 oz/d intake) and change in weight in adults. The plot shows 2 imputed studies with large standard errors and negative effect sizes. One of the studies had a p-value >0.10 and one with p =0.01.

#### Increase or no change in SSB intake versus decrease in SSB intake

In addition to the main analysis of the relationship between change in SSB intake, measured categorically (increase or no change in SSB intake versus decrease in intake), and change in weight in adults (Table 7, Figure A 67), the subgroup analyses and meta-regressions are summarized in Table A 15. Sex moderated the association between change in SSB intake and change in weight, but only one study did not combine across sexes. TEI also moderated the relationship, with a stronger association among TEI-adjusted results. However, the association was statistically significant for both TEI-adjusted and TEI-unadjusted results. Age, self-reported weight, and duration between exposure and outcome assessments were not associated with the relationship of interest. No subgroup analysis by juice content was completed because no studies reported including juice in the SSB measure.

Figure A 67 Meta-analysis of change in SSB (categorical, increase versus no change or decrease in intake) and change in weight (kg) in adults*

* CI: confidence interval; kg: kilogram; ML: multilevel; mo: month; PI: prediction interval; Q: quartile; SSB: sugar-sweetened beverage; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of change in SSB (measured categorically as increase or no change versus decrease in SSB intake) and change in weight in adults. Overall, weight increases by 0.75 (95% CI: 0.40, 1.09) kg in adults with increased or no change in SSB intake.

Table A 24 Summary of subgroup analyses for change in SSB (categorical, increase versus no change or decrease in intake) and change in weight (kg) in adults^*^ * β: slope; CI: confidence interval; NA: not applicable; NR: not reported; ref: reference; SSB: sugar-sweetened beverage(s); TEI: total energy intake; vs: versus

Subgroup Analysis; Comparison | Test of Subgroup Differences; β (95% CI), p-value | Model Summary of Subgroup 1; β (95% CI), p-value | Model Summary of Subgroup 2; β (95% CI), p-value | Model Summary of Subgroup 3; β (95% CI), p-value
Age at Exposure; NA (time between baseline and follow-up modeled continuously) | 0.007 (−0.08, 0.09), p=0.87 | NA | NA | NA
TEI; TEI adjusted vs Unadjusted (ref) | 0.54 (0.30, 0.77), p<0.01 | [underlined: TEI unadjusted]; 0.41 (0.22, 0.60), p<0.01 | [underlined: TEI adjusted]; 0.94 (0.80, 1.08), <0.01 | NA
Juice in SSB measure; Includes juice vs No juice reported (ref) | 0.25 (−0.61, 1.12), p=0.57 | [underlined: No juice reported]; 0.67 (0.19, 1.15), p=0.006 | [underlined: Includes juice]; NR (All data points from single study) | NA
Sex; Females vs All (ref); Males vs All (ref) | −0.52 (−0.77, −0.28), p<0.01 NA | [underlined: All]; 0.92 (0.79, 1.06), p<0.01 | [underlined: Females]; NR (All data points from single study) | [underlined: Males]; NA (No data points)
Duration of follow-up; NA (time between baseline and follow-up modeled continuously) | 0.02 (−0.16, 0.20), p=0.83 | NA | NA | NA
Self-reported weight; Self-reported vs Measured (ref) | −0.20 (−1.0, 0.60), p=0.62 | [underlined: Study-measured]; 0.66 (0.16, 1.17), p=0.01 | [underlined: Self-reported]; 0.87 (0.26, 1.48), p=0.005 | NA

Egger’s test showed statistically significant asymmetry (p=0.04), which may indicate non-reporting bias or heterogeneity. The latter is suggested by several subgroup analyses. The contoured funnel plot of the main analysis for change in SSB intake measured categorically (increase or no change in SSB intake versus decrease in intake) and change in weight in adults is depicted in Figure A 68. The trim and fill method suggests 1 missing study, indicating potential publication bias. The hypothetical missing study would be imprecise as it mirrors an extreme and imprecise observed value.

Figure A 68 Contoured funnel plot of slopes for change in SSB (categorical, increase versus no change or decrease in intake) and change in weight (kg) in adults

This figure shows a contoured funnel plot of slopes for change in SSB intake (measured continuously, per 12 oz/d intake) and change in weight in adults. The plot shows 1 imputed study with a large standard error, negative effect size, and a p-value >0.05.

### SSB intake at baseline and change in weight in adults

#### Continuous SSB intake

In addition to the main analyses reported in Table 7 and Figure A 69, the following subgroup analyses and meta-regressions for SSB intake at baseline (continuous) and change in weight in adults were conducted: by age at exposure (Figure A 70), by sex (Figure A 71), by TEI adjustment (Figure A 72), duration between exposure and outcome assessments (Figure A 73), and whether the outcome was self-reported (Figure A 74). There were no statistically significant moderating effects, but there were few observations in each subgroup. No subgroup analysis by juice content was completed because no studies reported including juice in the SSB measure.

Figure A 69 Meta-analysis of SSB at baseline (continuous, 12 oz/d) and change in weight (kg) in adults*

* CI: confidence interval; d: day; kg: kilogram; oz: ounce; PI: prediction interval; RE: random effects; SSB: sugar-sweetened beverage; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of SSB at baseline (measured continuously, per 12 oz/d intake) and change in weight in adults. Overall, weight increases by 0.05 (95% CI: 0.01, 0.09) kg in adults with each additional increase of 12 oz/d SSB.

Figure A 70 Meta-analysis of SSB at baseline (continuous, 12 oz/d) and change in weight (kg) in adults, by age at exposure*

* CI: confidence interval; d: day; kg: kilogram; ML: multilevel; oz: ounce; PI: prediction interval; SSB: sugar-sweetened beverage; y: year; vertical dotted line shows null effect

This figure shows a forest plot that demonstrates that age at exposure is not associated with the relationship between SSB at baseline (measured continuously, per 12 oz/d intake) and change in weight in adults.

Figure A 71 Meta-analysis of SSB at baseline (continuous, 12 oz/d) and change in weight (kg) in adults, by sex*

* CI: confidence interval; d: day; kg: kilogram; ML: multilevel; oz: ounce; PI: prediction interval; SSB: sugar-sweetened beverage; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of SSB at baseline (measured continuously, per 12 oz/d intake) and change in weight in adults, by sex. The plot shows that results in only females or only in males do not significantly differ from those in mixed samples. In males only, there is a statistically significant increase in weight in adults with each additional increase of 12 oz/d SSB; in females only, the 95% CI crosses 0. Only 1 study included a combined sample.

Figure A 72 Meta-analysis of SSB at baseline (continuous, 12 oz/d) and change in weight (kg) in adults, by TEI*

* Adj: adjusted; CI: confidence interval; d: day; kg: kilogram; oz: ounce; PI: prediction interval; RE: random effects’ SSB: sugar-sweetened beverage; TEI: total energy intake; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of SSB at baseline (measured continuously, per 12 oz/d intake) and change in weight in adults, by TEI adjustment. The plot shows that TEI-adjusted results do not significantly differ from TEI-unadjusted results. In the TEI-unadjusted subgroup, there is a statistically significant increase in weight in adults with each additional increase of 12 oz/d SSB; in the TEI-adjusted results trend in the same direction, but the 95% CI crosses 0.

Figure A 73 Meta-analysis of SSB at baseline (continuous, 12 oz/d) and change in weight (kg) in adults, by duration between exposure and outcome assessment*

* CI: confidence interval; d: day; kg: kilogram; oz: ounce; PI: prediction interval; RE: random effects; SSB: sugar-sweetened beverage; y: year; vertical dotted line shows null effect

This figure shows a forest plot that demonstrates that duration between exposure and outcome assessment is not associated with the relationship between SSB at baseline (measured continuously, per 12 oz/d intake) and change in weight in adults.

Figure A 74 Meta-analysis of SSB at baseline (continuous, 12 oz/d) and change in weight (kg) in adults, by self-reported outcome*

* CI: confidence interval; d: day; kg: kilogram; oz: ounce; PI: prediction interval; RE: random effects; SSB: sugar-sweetened beverage; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of SSB at baseline (measured continuously, per 12 oz/d intake) and change in weight in adults, by self-reported outcome. The plot shows that self-reported results do not significantly differ from staff-measured results. In both the staff-measured subgroup, there is a statistically significant increase in weight in adults with each additional increase of 12 oz/d SSB; only 1 study included self-reported results.

#### Some SSB intake versus less intake

In addition to the main analysis of the relationship between SSB intake at baseline, measured categorically (some SSB intake versus less intake), and change in weight in adults (Table 7, Figure A 75), the subgroup analyses and meta-regressions are summarized in Table A 16. Age at exposure moderated the association between SSB intake at baseline and change in weight. TEI adjustment, juice content, sex, duration between exposure and outcome assessments, and self-reported weight were not associated with the relationship of interest.

Figure A 75 Meta-analysis of SSB at baseline (categorical, some versus less intake) and change in weight (kg) in adults*

* CI: confidence interval; d: day; kg: kilogram; ML: multilevel; oz: ounce; PI: prediction interval; SSB: sugar-sweetened beverage; vs: versus; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of SSB at baseline (measured categorically as some versus less SSB intake) and change in weight in adults. Overall, change it weight did not differ between intake groups: 0.82 (95% CI: −0.07, 1.72) kg in adults.

Table A 25 Summary of subgroup analyses for SSB at baseline (categorical, some versus less intake) and change in weight (kg) in adults^*^ * β: slope; CI: confidence interval; NA: not applicable; NR: not reported; ref: reference; SSB: sugar-sweetened beverage(s); TEI: total energy intake; vs: versus

Subgroup Analysis; Comparison | Test of Subgroup Differences; β (95% CI), p-value | Model Summary of Subgroup 1; β (95% CI), p-value | Model Summary of Subgroup 2; β (95% CI), p-value | Model Summary of Subgroup 3; β (95% CI), p-value
Age at Exposure; NA (time between baseline and follow-up modeled continuously) | β=0.002 (0.000, 0.004), p=0.02 | NA | NA | NA
TEI; TEI adjusted vs Unadjusted (ref) | −0.93 (−2.73, 0.86), p=0.31 | [underlined: TEI unadjusted]; 0.76 (−0.05, 1.57), p=0.07 | [underlined: TEI adjusted]; NR (All data points from single study) | NA
Juice in SSB measure; Includes juice vs No juice reported (ref) | 0.31 (−2.25, 2.87), p=0.82 | [underlined: No juice reported]; 0.79 (−0.54, 2.13), p=0.25 | [underlined: Includes juice]; NR (All data points from single study) | NA
Sex; Females vs All (ref); Males vs All (ref) | 0.18 (−2.18, 2.55), p=0.88; 0.25 (−2.11, 2.62), p=0.83 | [underlined: All]; 0.86 (0.25, 1.48), p=0.01 | [underlined: Females]; 0.86 (0.25, 1.48), p=0.01 | [underlined: Males]; NR (All data points from single study)
Duration of follow-up; NA (time between baseline and follow-up modeled continuously) | −0.09 (−0.47, 0.30), p=0.67 | NA | NA | NA
Self-reported weight; Self-reported vs Measured (ref) | 0.31 (−2.25, 2.87), p=0.82 | [underlined: Study-measured]; 0.79 (−0.54, 2.13), p=0.25 | [underlined: Self-reported]; NR (All data points from single study) | NA

Egger’s test showed statistically significant asymmetry (p<0.01), which may indicate non-reporting bias or heterogeneity. The main analysis (Figure A 75) confirmed moderate slope heterogeneity between studies, and similarity of effects within all but one study (Mullie, 2017). The contoured funnel plot of the main analysis for SSB intake at baseline (measured categorically as some versus less intake) and change in weight is depicted in Figure A 76. The trim and fill method suggests 3 missing studies, including 2 significant studies, which indicates potential publication bias. These potential studies would be relatively small with large negative slopes.

Figure A 76 Contoured funnel plot of slopes for SSB at baseline (categorical, some versus less intake) and change in weight (kg) in adults

This figure shows a contoured funnel plot summarizing the meta-analysis of SSB at baseline (measured categorically as some versus less SSB intake) and change in weight in adults. The plot shows 3 imputed studies with large standard errors and negative effect sizes. Two studies had p-values >0.05 and one had p=0.01.

### RCT-SSB intervention and change in weight in adults

In addition to the main analysis reported above (Table 7) and in Figure A 77, the subgroup analysis for SSB interventions on change in weight in adults was conducted by comparator (Figure A 78). Subgroup analyses by sex, and TEI adjustment were not conducted due to lack of variation in the evidence. Meta-regressions showed that neither age at exposure (in years) nor trial duration (in years) significantly relate to the SSB interventions’ impact on average weight change: β_age_=-0.03 (95% CI: −0.07, 0.02), p=0.24; β_duration_=-0.66 (95% CI: −1.54, 0.22), p=0.14.

Figure A 77 Meta-analysis of SSB intervention and change in weight in adults*

* CI: confidence interval; LNCSB: low- and no-calorie sweetened beverage; ML: multilevel; PI: prediction interval; SD: standard deviation; SMD: standard mean difference; SSB: sugar-sweetened beverage; USB: unsweetened beverage; vs: versus; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of SSB intervention and change in weight in adults. Overall, interventions to decrease SSB did not significantly impact weight change: 0.21 (−0.06, 0.48) kg.

Figure A 78 Meta-analysis of SSB intervention and change in weight in adults, by comparator^†^

^†^ CI: confidence interval; LNCSB: low- and no-calorie sweetened beverage; ML: multilevel; PI: prediction interval; SD: standard deviation; SMD: standard mean difference; SSB: sugar-sweetened beverage; USB: unsweetened beverage; vs: versus; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of SSB intervention and change in weight in adults, by comparator. The plot shows that results for unsweetened beverage comparators do not significantly differ from results for low- or no-calorie sweetened beverage comparators. In both subgroups, the 95% CI crosses 0.

Egger’s test showed non-significant asymmetry (p=0.43), which may indicate a lack of reporting bias or homogeneity; however, homogeneity is unlikely given the analyses reported above. The contoured funnel plot of the main analysis for SSB intervention on change in weight in adults is depicted in Figure A 79. The trim and fill method does not indicate any potentially missing studies.

Figure A 79 Contoured funnel plot of SSB intervention and change in weight in adults

This figure shows a contoured funnel plot summarizing the meta-analysis of SSB intervention and change in weight in adults. The plot shows 0 imputed studies.

### Change in SSB intake and change in waist circumference in adults

#### Continuous SSB intake

In addition to the main analysis reported above (Table 7) and in Figure A 80, the following subgroup analyses and meta-regressions for change in SSB intake (continuous) and change in waist circumference in adults were conducted: by age at exposure (Figure A 81), by sex (Figure A 82), by self-reported weight (Figure A 83), by total energy intake (Figure A 84), by juice (Figure A 85) and by duration between exposure and outcome assessment (Figure A 86). The subgroup analysis of self-reported versus measured waist circumference had the only statistically significant test, but with few observations in all subgroups, these tests should be interpreted with caution.

Figure A 80 Meta-analysis of change in SSB (continuous, 12 oz/d) and change in waist circumference in adults*

* CI: confidence interval; cm: centimeter; d: daily; oz: ounce; PI: prediction interval; RE: random effects; SSB: sugar-sweetened beverage; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of change in SSB (measured continuously, per 12 oz/d intake) and change in waist circumference in adults. Overall, there was not a statistically significant difference in the change in waist circumference by change in SSB intake: 0.38 (95% CI: −0.06, 0.81) cm.

Figure A 81 Meta-analysis of change in SSB (continuous, 12 oz/d) and change in waist circumference in adults, by age at exposure*

* CI: confidence interval; cm: centimeter; d: daily; ML: multilevel; oz: ounce; PI: prediction interval; SSB: sugar-sweetened beverage; y: year; vertical dotted line shows null effect

This figure shows a forest plot that demonstrates that age at exposure is not associated with the relationship between change in SSB (measured continuously, per 12 oz/d intake) and change in waist circumference in adults.

Figure A 82 Meta-analysis of change in SSB (continuous, 12 oz/d) and change in waist circumference in adults, by sex*

* CI: confidence interval; cm: centimeter; d: daily; oz: ounce; PI: prediction interval; RE: random effects; SSB: sugar-sweetened beverage; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of change in SSB (measured continuously, per 12 oz/d intake) and change in waist circumference in adults, by sex. The plot shows that results in only females or only in males do not significantly differ from those in mixed samples. In males and in females, the 95% CI crosses 0. Only 1 study included a combined sample.

Figure A 83 Meta-analysis of change in SSB (continuous, 12 oz/d) and change in waist circumference in adults, by self-reported outcome*

* CI: confidence interval; cm: centimeter; d: daily; oz: ounce; PI: prediction interval; RE: random effects; SSB: sugar-sweetened beverage; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of change in SSB (measured continuously, per 12 oz/d intake) and change in waist circumference in adults, by self-reported outcome. Results for self-reported results are statistically different from staff-measured results, although only one study included self-reported results. In the staff-measured subgroup, the 95% CI crosses 0.

Figure A 84 Meta-analysis of change in SSB (continuous, 12 oz/d) and change in waist circumference in adults, by TEI*

* CI: confidence interval; cm: centimeter; d: daily; oz: ounce; PI: prediction interval; RE: random effects; SSB: sugar-sweetened beverage; TEI: total energy intake; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of change in SSB (measured continuously, per 12 oz/d intake) and change in waist circumference in adults, by TEI adjustment. The plot shows that TEI-adjusted results do not significantly differ from TEI-unadjusted results. In the TEI-unadjusted subgroup, the 95% CI crosses 0; only 1 study reported TEI-adjusted results.

Figure A 85 Meta-analysis of change in SSB (continuous, 12 oz/d) and change in waist circumference in adults, by juice content*

* CI: confidence interval; cm: centimeter; d: daily; oz: ounce; RE: random effects; PI: prediction interval; SSB: sugar-sweetened beverage; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of change in SSB (measured continuously, per 12 oz/d intake) and change in waist circumference in adults, by juice content. The plot shows that results that include juice in the SSB measure do not significantly differ from those that do not report including juice. When no juice was reported, the 95% CI crosses 0; only 1 study reported including juice in the SSB measure.

Figure A 86 Meta-analysis of change in SSB (continuous, 12 oz/d) and change in waist circumference in adults, by duration between exposure and outcome assessment*

* CI: confidence interval; cm: centimeter; d: daily; f/u: follow-up; oz: ounce; PI: prediction interval; RE: random effects; SSB: sugar-sweetened beverage; vertical dotted line shows null effect

This figure shows a forest plot that demonstrates that duration between exposure and outcome assessment is not associated with the relationship between change in SSB (measured continuously, per 12 oz/d intake) and change in waist circumference in adults.

### SSB intake at baseline and change in waist circumference in adults

#### Continuous SSB intake

In addition to the main analysis reported above (Table 7) and in Figure A 87, the following subgroup analyses and meta-regressions for change in SSB intake at baseline (continuous) and change in waist circumference in adults were conducted: by age at exposure (Figure A 88), by sex (Figure A 89), by self-reported weight (Figure A 90), by total energy intake (Figure A 91), and by duration between exposure and outcome assessment (Figure A 92). None of these tests were statistically significant. A subgroup analysis by juice content was not conducted because no studies reported included fruit juice in the SSB measure.

Figure A 87 Meta-analysis of SSB at baseline (continuous, 12 oz/d) and change in waist circumference in adults*

* CI: confidence interval; cm: centimeter; d: day; ML: multilevel; oz: ounce; PI: prediction interval; SSB: sugar-sweetened beverage; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of SSB at baseline (measured continuously, per 12 oz/d intake) and change in waist circumference in adults. Overall, there was not a statistically significant difference in the change in waist circumference by SSB intake at baseline: 0.09 (95% CI: −0.00, 0.18) cm.

Figure A 88 Meta-analysis of SSB at baseline (continuous, 12 oz/d) and change in waist circumference in adults, by age at exposure*

* CI: confidence interval; cm: centimeter; d: day; ML: multilevel; oz: ounce; PI: prediction interval; SSB: sugar-sweetened beverage; y:year; vertical dotted line shows null effect

This figure shows a forest plot that demonstrates that age at exposure is not associated with the relationship between SSB at baseline (measured continuously, per 12 oz/d intake) and change in waist circumference in adults.

Figure A 89 Meta-analysis of SSB at baseline (continuous, 12 oz/d) and change in waist circumference in adults, by sex*

* CI: confidence interval; cm: centimeter; d: day; PI: prediction interval; RE: random effects; SSB: sugar-sweetened beverage; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of SSB at baseline (measured continuously, per 12 oz/d intake) and change in waist circumference in adults, by sex. The plot shows that results in only females or only in males do not significantly differ from those in mixed samples. In males and in females, change in waist circumference increases with each additional 12 oz/d SSB at baseline. Only 1 study included a combined sample.

Figure A 90 Meta-analysis of SSB at baseline (continuous, 12 oz/d) and change in waist circumference in adults, by self-reported outcome*

* CI: confidence interval; cm: centimeter; d: day; ML: multilevel; PI: prediction interval; RE: random effects; SSB: sugar-sweetened beverage; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of SSB at baseline (measured continuously, per 12 oz/d intake) and change in waist circumference in adults, by self-reported outcome. The plot shows that self-reported results do not significantly differ from staff-measured results. In both subgroups, change in waist circumference increases with each additional 12 oz/d SSB at baseline.

Figure A 91 Meta-analysis of SSB at baseline (continuous, 12 oz/d) and change in waist circumference in adults, by TEI*

* adj: adjusted; CI: confidence interval; cm: centimeter; d: day; PI: prediction interval; RE: random effects; SSB: sugar-sweetened beverage; TEI: total energy intake; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of SSB at baseline (measured continuously, per 12 oz/d intake) and change in waist circumference in adults, by TEI adjustment. The plot shows that TEI-adjusted results do not significantly differ from TEI-unadjusted results. In both subgroups, change in waist circumference increases with each additional 12 oz/d SSB at baseline.

Figure A 92 Meta-analysis of SSB at baseline (continuous, 12 oz/d) and change in waist circumference in adults, by duration between exposure and outcome assessment*

* CI: confidence interval; cm: centimeter; d: day; f/u: follow-up; ML: multilevel; PI: prediction interval; SSB: sugar-sweetened beverage; y: year; vertical dotted line shows null effect

This figure shows a forest plot that demonstrates that duration between exposure and outcome assessment is not associated with the relationship between SSB at baseline (measured continuously, per 12 oz/d intake) and change in waist circumference in adults.

### SSB intake at baseline and risk of obesity at follow-up in adults

#### More SSB intake versus less intake

In addition to the main analysis reported below (Figure A 93), the following subgroup analyses for SSB intake (also measured categorical, more versus less or none) at baseline and risk of obesity (including abdominal obesity) at follow-up among adults were conducted and presented in Table A 17 and the subgroup analyses’ findings do not change the interpretation of the main analysis.

Figure A 93 Meta-analysis of SSB at baseline (categorical, more versus less or no intake) and overweight and/or obesity, including abdominal obesity, at follow-up in adults*

* CI: confidence interval; d: day; ML: multilevel; NR: not reported; OR: odds ratio; PI: prediction interval; ref: reference; SSB: sugar-sweetened beverage; vs: versus; wk: week; y: year; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of SSB at baseline (measured categorically as more versus less) and risk of obesity in adults. Overall, odds of obesity was 1.35 (95% CI: 1.16, 1.56) in adults consuming more SSB.

Table A 26 Summary of subgroup analyses for SSB at baseline (categorical, more versus less or no intake) and overweight and/or obesity, including abdominal obesity, at follow-up in adults^*^ * CI: confidence interval; NA: not applicable; NR: not reported; OR: odds ratio; ref: reference; SSB: sugar-sweetened beverage(s); TEI: total energy intake; vs: versus

Subgroup Analysis; Comparison | Test of Subgroup Differences; OR (95% CI), p-value | Model Summary of Subgroup 1; OR (95% CI), p-value | Model Summary of Subgroup 2; OR (95% CI), p-value | Model Summary of Subgroup 3; OR (95% CI), p-value
TEI; TEI adjusted vs Unadjusted (ref) | 0.76 (0.60, 0.97), p=0.03 | [underlined: TEI unadjusted]; 1.63 (1.31, 2.02), p<0.0001 | [underlined: TEI adjusted]; 1.24 (1.10, 1.39), p=0.0003 | NA
Juice in SSB measure; Includes juice vs No juice reported (ref) | 1.31 (1.03, 1.68), p=0.03 | [underlined: No juice reported]; 1.24 (1.11, 1.40), p=0.0002 | [underlined: Includes juice]; NR (All data points from single study) | NA
Sex; Females vs All (ref); Males vs All (ref) | 1.30 (1.03, 1.63), p=0.02; 1.02 (0.68, 1.52), p=0.92 | [underlined: All]; 1.21 (1.07, 1.38), p=0.004 | [underlined: Females]; 1.57 (1.31, 1.89), p<0.0001 | [underlined: Males]; 1.24 (0.85, 1.81), p=0.27
Duration of Follow-up; NA (time between baseline and follow-up modeled continuously) | 0.97 (0.91, 1.04), p=0.45 | NA | NA | NA
Self-reported obesity; Study measured vs Self-report (ref) | 0.97 (0.69, 1.37), p=0.87 | [underlined: Self-report]; 1.33 (1.11, 1.59), p=0.002 | [underlined: Study measured]; 1.33 (1.11, 1.59), p=0.002 | NA
Outcome; Obesity vs Abdominal obesity (ref) | 1.19 (0.98, 1.44), p=0.08 | [underlined: Abdominal obesity]; 1.25 (1.12, 1.39), p<0.0001 | [underlined: Obesity]; 1.48 (1.21, 1.81), p=0.0002 | NA

The Egger’s test showed no statistically significant asymmetry (p=0.09), which may indicate a lack of non-reporting bias or of homogeneity. The contoured funnel plot of the main analysis for SSB intake at baseline (categorical, more versus less or none) and risk of obesity (including abdominal obesity) at follow-up in adults is depicted in Figure A 94. The trim and fill method does not suggest any statistically significant missing studies.

Figure A 94 Contoured funnel plot of slopes for SSB at baseline (categorical, more versus less or no intake) and overweight and/or obesity, including abdominal obesity, at follow-up in adults

This figure shows a contoured funnel plot summarizing the meta-analysis of SSB at baseline (measured categorically as more versus less) and risk of obesity in adults. The plot shows 1 imputed study with a large standard errors, negative effect size, and p-values >0.10.

### RCT-SSB intervention and change in BMI in adults

In addition to the main analysis reported above (Table 7) and in Figure A 95, a subgroup analysis for SSB interventions on change in BMI in adults was conducted by comparator (Figure A 96). No subgroup analyses by sex, or TEI adjustment were conducted due to lack of variation in the evidence. Meta-regressions showed that neither age at exposure (in years) nor trial duration (in years) significantly affect the relationship between SSB interventions and weight change: β_age_=0.004 (95% CI: −0.03, 0.04), p=0.80; β_duration_=0.06 (−0.63, 0.74), p=0.87.

Figure A 95 Meta-analysis of SSB intervention and change in BMI in adults*

* BMI: body mass index; CI: confidence interval; LNCSB: low- and no-calorie sweetened beverage; ML: multilevel; PI: prediction interval; SD: standard deviation; SMD: standard mean difference; SSB: sugar-sweetened beverage; USB: unsweetened beverage; vs: versus; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of SSB intervention and change in BMI in adults. Overall, interventions to replace SSB with unsweetened beverages or low- or no-calorie sweetened beverages result in 0.16 (0.01, 0.30) SD units lower BMI over time.

Figure A 96 Meta-analysis of SSB intervention and change in BMI in adults, by comparator*

* BMI: body mass index; CI: confidence interval; LNCSB: low- and no-calorie sweetened beverage; ML: multilevel; PI: prediction interval; SD: standard deviation; SMD: standard mean difference; SSB: sugar-sweetened beverage; USB: unsweetened beverage; vs: versus; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of SSB intervention and change in BMI in adults, by comparator. The plot shows that results for unsweetened beverage comparators do not significantly differ from results for low- or no-calorie sweetened beverage comparators. In both subgroups, the 95% CI crosses 0.

### RCT-SSB intervention and change in fat mass in adults

In addition to the main analysis reported above (Table 7) and in Figure A 97, the a subgroup analysis for SSB interventions on change in fat mass in adults was conducted by comparator (Figure A 98). No subgroup analyses by sex, or TEI adjustment were conducted due to lack of variation in the evidence. Meta-regressions showed that neither age at exposure (in years) nor trial duration (in years) significantly affect the relationship between SSB interventions and fat mass change: β_age_=0.01 (−0.02, 0.05), p=0.47; β_duration_=-0.23 (−0.70, 0.25), p=0.35.

Figure A 97 Meta-analysis of SSB intervention and change in fat mass in adults*

* CI: confidence interval; LNCSB: low- and no-calorie sweetened beverage; ML: multilevel; PI: prediction interval; SD: standard deviation; SMD: standard mean difference; SSB: sugar-sweetened beverage; USB: unsweetened beverage; vs: versus; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of SSB intervention and change in fat mass in adults. Overall, interventions to decrease SSB did not significantly impact fat mass change: 0.10 (−0.04, 0.25) SD units.

Figure A 98 Meta-analysis of SSB intervention and change in fat mass in adults, by comparator*

* CI: confidence interval; LNCSB: low- and no-calorie sweetened beverage; ML: multilevel; PI: prediction interval; SD: standard deviation; SMD: standard mean difference; SSB: sugar-sweetened beverage; USB: unsweetened beverage; vs: versus; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of SSB intervention and change in fat mass in adults, by comparator. The plot shows that results for unsweetened beverage comparators do not significantly differ from results for low- or no-calorie sweetened beverage comparators. In both subgroups, the 95% CI crosses 0.

The Egger’s test showed non-significant asymmetry (p=0.86), which may indicate a lack of non-reporting bias or homogeneity. The contoured funnel plot of the main analysis for SSB intervention on change in fat mass in adults is depicted in Figure A 99. The trim and fill method does not indicate any missing significant studies.

Figure A 99 Contoured funnel plot of SSB intervention and change in fat mass in adults

This figure shows a contoured funnel plot summarizing the meta-analysis of SSB intervention and change in fat mass in adults. The plot shows 0 imputed studies.