# Appendix 3 Inclusion and exclusion criteria comparison between existing and updated systematic reviews

Table A 3 Inclusion and exclusion criteria comparison between existing^*^ * Mayer-Davis E, Leidy H, Mattes R, Naimi T, Novotny R, Schneeman B, Kingshipp BJ, Spill M, Cole NC, Bahnfleth CL, Butera G, Terry N, Obbagy J. Beverage Consumption and Growth, Size, Body Composition, and Risk of Overweight and Obesity: A Systematic Review. July 2020. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: 10.52570/NESR.DGAC2020.SR0401 and updated systematic reviews for the research question: What is the relationship between sugar-sweetened beverages and growth, body composition, and risk of obesity?

Category | Existing Review | Updated Review | Change and Rationale
Study design | [underlined: Included]:; - Randomized controlled trials; - Non-randomized controlled trials (including quasi-experimental and controlled before and after studies); - Prospective cohort studies; - Retrospective cohort studies; - Nested case-control studies; - Mendelian randomization studies; [underlined: Excluded]:; - Uncontrolled trials; - Case-control studies; - Cross-sectional studies; - Uncontrolled before-and-after studies; - Narrative reviews; - Systematic reviews; - Meta-analyses | [underlined: Included]:; - Randomized controlled trials; - Non-randomized controlled trials^†^; † Including quasi-experimental and controlled before-and-after studies; - Prospective cohort studies; - Retrospective cohort studies; - Nested case-control studies; - Mendelian randomization studies; [underlined: Excluded]:; - Uncontrolled trials^‡^; ‡ Including uncontrolled before-and-after studies; - Case-control studies; - Cross-sectional studies; - Ecological studies; - Narrative reviews; - Systematic reviews; - Meta-analyses; - Modeling and simulation studies | No changes were made. Formatting was edited for clarity. Modeling and simulation studies, which were always excluded, were added explicitly to the exclude list.
Publication date | [underlined: Included]:; - January 2000 – June 2019 (Milk, 100% Juice, LNCSB); - January 2012 – June 2019 (SSB)^*^; * This publication date range criteria was applied to the review of SSB evidence because the 2015 Dietary Guidelines Advisory Committee reviewed evidence on the relationship between added sugars, including SSB, and body weight/obesity, published up to January 2012.; [underlined: Excluded]:; - Before January 2000, after June 2019 | [underlined: Included]:; - January 2000 – May 2023^†^; † This review update date range encompasses the original systematic review date range, which included articles published from January 2000 to June 2019; [underlined: Excluded]:; - Before January 2000, after May 2023 | Dates were modified to enable focus on the most recent evidence.
Population: Study participants | [underlined: Included]:; - Human; [underlined: Excluded]:; - Animal subjects; - Hospitalized samples | [underlined: Included]:; - Human; [underlined: Excluded]:; - Non-human | No change
Population: Life stage | [underlined: Included]:; - Age at intervention/exposure and outcome:; - Child (2–5 years); - Child (6–12 years); - Adolescents (13–18 years); - Adults (19 and older); - Older adults (65+ years); [underlined: Excluded]:; - Age at intervention/exposure and outcome: <2y | [underlined: Included]:; - At intervention/exposure and outcome:; - Children and adolescents (2 up to 19 years); - Adults and older adults (19 years and older); - Individuals during pregnancy; - Individuals during postpartum; [underlined: Excluded]:; - Infants and young children (birth up to 24 months) | Individuals during pregnancy and postpartum will be included in the updated review on dairy milk and milk alternatives rather than being addressed in separate questions.
Population: Health Status | [underlined: Included]:; - Studies that enroll participants who are healthy and/or at risk for chronic disease; - Studies that enroll some participants diagnosed with a disease; - Studies that enroll some participants who are classified as underweight, stunted, wasted, or obese; [underlined: Excluded]:; - Studies that exclusively enroll participants diagnosed with a disease, or hospitalized with an illness or injury; - Studies that exclusively enroll participants classified as obese (i.e., studies that aim to treat participants who have already been classified as obese) | [underlined: Included]:; - Studies that [underlined: exclusively] enroll participants not diagnosed with a disease^*^; * Studies that enroll participants who are at risk for chronic disease will be included; - Studies that enroll [underlined: some] participants:; - diagnosed with a disease;; - diagnosed with a disorder that affects feeding/eating or growth (e.g., autism spectrum disorder, attention-deficit/hyperactivity disorder, eating disorder);; - with severe undernutrition, failure to thrive/underweight, stunting, or wasting;; - who became pregnant using Assisted Reproductive Technologies;; - with multiple gestation pregnancies;; - receiving pharmacotherapy to treat obesity;; - pre- or post-bariatric surgery;; - and/or hospitalized for an illness, injury, or surgery; [underlined: Excluded]:; - Studies that [underlined: exclusively] enroll participants:; - diagnosed with a disease;^†^; † Studies that exclusively enroll participants with obesity will be included; - diagnosed with a disorder that affects feeding/eating or growth (e.g., autism spectrum disorder, attention-deficit/hyperactivity disorder, eating disorder);; - with severe undernutrition, failure to thrive/underweight, stunting, or wasting;; - who became pregnant using Assisted Reproductive Technologies;; - with multiple gestation pregnancies;; - receiving pharmacotherapy to treat obesity;; - pre- or post-bariatric surgery;; - and/or hospitalized for an illness, injury, or surgery^‡^; ‡ Studies that exclusively enroll participants post-cesarean section will be included | Study samples where 100% of participants have obesity will be included
Intervention/exposure | [underlined: Included]:; Type and amount of beverage consumption of the following beverage types:; - Milk (dairy milk and milk substitutes, including flavored milk); - 100% Juice; - Low- or no-calorie sweetened beverages (LNCSB); - Sugar-sweetened beverages (SSB); [underlined: Excluded]:; - Other beverage types, including: Coffee, tea, water, and nutritional beverages (e.g., protein shakes, smoothies); - Studies focusing on specific nutrients added to beverages instead of a beverage as a whole (i.e., studies where beverages are the delivery mechanism for a nutrient); - Beverages that are not commercially available (e.g., experimentally manipulated beverages); - Supplements; - Alcohol; - Soups | [underlined: Included]:; - Dairy milk and milk alternative consumption; - Multi-component intervention in which the isolated effect of the intervention of interest on the outcome(s) of interest is provided or can be determined despite multiple components; [underlined: Excluded]:; - Infant milk, infant formula, toddler formula/milks; - Other beverage types, such as nutritional beverages (e.g., protein shakes, smoothies); - Studies focusing on specific nutrients added to beverages instead of a beverage as a whole (i.e., studies where beverages are the delivery mechanism for a nutrient); - Beverages that are not commercially available (e.g., experimentally manipulated beverages); - Supplements; - Alcohol; - Soups; - Multi-component intervention in which the isolated effect of the intervention of interest on the outcome(s) of interest is not provided or cannot be determined due to multiple components | The existing systematic review conducted by the 2020 Dietary Guidelines Advisory Committee (Committee) examined multiple beverages: milk, 100% juice, LNCSB, and SSB.; The proposed question will update the review of dairy milk and milk alternatives, which will be examined as an individual systematic review.
Comparator | [underlined: Included]:; - Different amount of the same beverage (including no consumption and versions diluted with water); - Beverage vs. solid; - Beverage vs. water; - Sugar-sweetened beverages vs. low- or no-calorie sweetened beverages; - Dairy milk with different amounts of fat; [underlined: Excluded]:; - No comparator; - Studies comparing different types of beverages (with the exception of studies comparing a beverage to plain water, dairy milk with different amounts of fat, and sugar-sweetened beverages to low- or no-calorie sweetened beverages) | [underlined: Included]:; - Consumption of a different amount of dairy milk and milk alternatives; - Dairy milk and milk alternatives vs. water; - Dairy milk and milk alternatives with different amounts of fat and/or sweetener; [underlined: Excluded]:; - No comparator | No change
Outcome(s) | [underlined: Included]:; - Weight, weight-for-age; - Height, length/stature-for-age; - BMI, BMI z-score, weight-for-length; - Body circumferences: head, arm, waist, thigh, neck; - Body composition and distribution (e.g., % fat mass, % fat free mass); - Incidence and prevalence of:; - Underweight, failure to thrive, stunting, wasting; - Healthy weight; - Overweight; - Obesity; [underlined: Excluded]; - N/A | [underlined: Included]:; Growth (in children, adolescents):; - Height; - Length; - Weight; - Stunting, failure to thrive, wasting; - BMI-for-age; - Body circumference (arm, neck, thigh); Body composition (in children, adolescents, adults, older adults):; - Skinfold thickness; - Fat mass, ectopic fat; - Fat-free mass or lean mass; - Waist circumference, waist-to-hip-ratio; Risk of obesity (in children, adolescents, adults, older adults):; - BMI; - Underweight; - Normal weight; - Overweight and/or obesity; - Weight gain; - Weight loss and maintenance (in adults, older adults); Pregnancy and postpartum-related weight change; - Adequacy of total gestational weight gain (i.e., in relation to recommendations based on prepregnancy BMI); - Postpartum weight change (during postpartum); [underlined: Excluded]; - N/A | The existing systematic review conducted by the 2020 Dietary Guidelines Advisory Committee (Committee) examined growth, size, body composition, and risk of overweight and obesity.; The proposed question will update the relationships examined by the 2020 Committee and expand that work by including additional outcomes of weight loss and maintenance. This expansion was recommended by the 2020 Committee, Federal stakeholders, and the public. In addition, gestational weight gain and postpartum weight change will be included in the updated review rather than addressed in separate systematic review questions.
Study duration | [underlined: Included]; - N/A; [underlined: Excluded]; - N/A | [underlined: Included]; - Intervention length ≥12 weeks (in children, adolescents, adults, and older adults only); [underlined: Excluded]; - Intervention length <12 weeks (in children, adolescents, adults, and older adults only) | Study duration criteria were developed to enable focus on a stronger body of evidence.
Publication status | [underlined: Included]; - Articles published in peer-reviewed journals; [underlined: Excluded]; - Articles not published in peer-reviewed journals, including unpublished data, manuscripts, reports, pre-prints, abstracts, and conference proceedings | [underlined: Included]; - Peer-reviewed articles published in research journals; [underlined: Excluded]; - Non-peer-reviewed articles, unpublished data or manuscripts, pre-prints, reports, editorials, retracted articles, and conference abstracts or proceedings | No change
Language | [underlined: Included]; - Articles published in English; [underlined: Excluded]; - Articles published in language other than English | [underlined: Included]; - Published in English; [underlined: Excluded]; - Not published in English | No change
Country^*^; * In order to determine the inclusion exclusion criteria for country, the Human Development classification was used. This classification is based on the Human Development Index (HDI) ranking from the year the study intervention occurred or data were collected (UN Development Program. HDI 1990-2017 HDRO calculations based on data from UNDESA (2017a), UNESCO Institute for Statistics (2018), United Nations Statistics Division (2018b), World Bank (2018b), Barro and Lee (2016) and IMF (2018). Available from: http://hdr.undp.org/en/data). If the study did not report the year in which the intervention occurred or data were collected, the HDI classification for the year of publication was applied. HDI values are available from 1980, and then from 1990 to present. If a study was conducted prior to 1990, the HDI classification from 1990 was applied. If a study was conducted in 2018 or 2019, the most current HDI classification was applied. When a country was not included in the HDI ranking, the current country classification from the World Bank was used instead (The World Bank. World Bank country and lending groups. Available from: https://datahelpdesk.worldbank.org/knowledgebase/articles/906519-world-country-and-lending-groups) | [underlined: Included]; - Studies conducted in very high or high Human Development countries; [underlined: Excluded]; - Studies conducted in medium or lower Human Development countries | [underlined: Included]; - Studies conducted in countries classified as high or very high on the Human Development Index the year(s) the intervention/exposure data were collected; [underlined: Excluded]; - Studies conducted in countries classified as medium or low on the Human Development Index the year(s) the intervention/exposure data were collected | Clarification added that Human Development Index classification is based on the year(s) when intervention/exposure data were collected.