# Appendix 2 Conclusion statements from the existing systematic review

Table A 2 Conclusion statements from the existing systematic review for the research question: What is the relationship between sugar-sweetened beverage consumption and growth, body composition, and risk of obesity?

Citation | Conclusion statements and grades
Mayer-Davis E, Leidy H, Mattes R, Naimi T, Novotny R, Schneeman B, Kingshipp BJ, Spill M, Cole NC, Bahnfleth CL, Butera G, Terry N, Obbagy J. Beverage Consumption and Growth, Size, Body Composition, and Risk of Overweight and Obesity: A Systematic Review. July 2020. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: 10.52570/NESR.DGAC2020.SR0401 | Moderate evidence suggests that higher sugar-sweetened beverage intake is associated with greater adiposity in children. (Grade: Moderate); Insufficient evidence is available to determine the relationship between sugar-sweetened beverages compared with low- and no- calorie sweetened beverages on adiposity in children. (Grade: Grade Not Assignable); Limited evidence suggests that higher sugar-sweetened beverage intake is associated with greater adiposity in adults. (Grade: Limited); Limited evidence suggests no association between sugar-sweetened beverages compared with low- and no - calorie sweetened beverages on adiposity in adults. (Grade: Limited)