# References of the articles included in the systematic review

1 Arima K, Zhong R, Ugai T, . Western-Style Diet, pks Island-Carrying Escherichia coli, and Colorectal Cancer: Analyses From Two Large Prospective Cohort Studies. Gastroenterology. Oct 2022;163(4):862–874. doi:10.1053/j.gastro.2022.06.054 35760086
2 Arthur RS, Kirsh VA, Rohan TE. The association of the healthy eating index with risk of colorectal cancers (overall and by subsite) among Canadians. Cancer Epidemiol. Dec 2023;87:102454. doi:10.1016/j.canep.2023.102454 37879292
3 Barrubes L, Babio N, Hernandez-Alonso P, . Association between the 2018 WCRF/AICR and the Low-Risk Lifestyle Scores with Colorectal Cancer Risk in the Predimed Study. J Clin Med. Apr 23 2020;9(4)doi:10.3390/jcm9041215
4 Castello A, Rodriguez-Barranco M, Fernandez de Larrea N, . Adherence to the Western, Prudent and Mediterranean Dietary Patterns and Colorectal Cancer Risk: Findings from the Spanish Cohort of the European Prospective Investigation into Cancer and Nutrition (EPIC-Spain). Nutrients. Jul 27 2022;14(15)doi:10.3390/nu14153085
5 Chaltiel D, Julia C, Chaltiel R, . Prospective association between adherence to the 2017 French dietary guidelines and risk of death, CVD and cancer in the NutriNet-Sante cohort. Br J Nutr. Feb 28 2022;127(4):619–629. doi:10.1017/S0007114521001367 34016201
6 Chang K, Gunter MJ, Rauber F, . Ultra-processed food consumption, cancer risk and cancer mortality: a large-scale prospective analysis within the UK Biobank. EClinicalMedicine. Feb 2023;56:101840. doi:10.1016/j.eclinm.2023.101840 36880051
7 Chebet JJ, Thomson CA, Kohler LN, . Association of Diet Quality and Physical Activity on Obesity-Related Cancer Risk and Mortality in Black Women: Results from the Women’s Health Initiative. Cancer Epidemiol Biomarkers Prev. Mar 2020;29(3):591–598. doi:10.1158/1055-9965.EPI-19-1063 31915146
8 Hoang T, Cho S, Choi JY, Kang D, Shin A. Assessments of dietary intake and polygenic risk score in associations with colorectal cancer risk: evidence from the UK Biobank. BMC Cancer. Oct 18 2023;23(1):993. doi:10.1186/s12885-023-11482-1 37853340
9 Jin Q, Shi N, Lee DH, . Hyperinsulinemic and Pro-Inflammatory Dietary Patterns and Metabolomic Profiles Are Associated with Increased Risk of Total and Site-Specific Cancers among Postmenopausal Women. Cancers (Basel). Mar 14 2023;15(6)doi:10.3390/cancers15061756
10 Kim J, Boushey CJ, Wilkens LR, Haiman CA, Le Marchand L, Park SY. Plant-based dietary patterns defined by a priori indices and colorectal cancer risk by sex and race/ethnicity: the Multiethnic Cohort Study. BMC Med. Nov 29 2022;20(1):430. doi:10.1186/s12916-022-02623-7 36443779
11 Kim J, Khil J, Kim H, Keum N, Zhang X, Giovannucci E. Plant-based dietary patterns and the risk of digestive system cancers in 3 large prospective cohort studies. Eur J Epidemiol. Jun 2023;38(6):617–627. doi:10.1007/s10654-023-01007-2 37101016
12 Lee DH, Jin Q, Shi N, . Dietary Inflammatory and Insulinemic Potentials, Plasma Metabolome and Risk of Colorectal Cancer. Metabolites. Jun 12 2023;13(6)doi:10.3390/metabo13060744
13 Liu F, Lv Y, Peng Y, . Plant-based dietary patterns, genetic predisposition and risk of colorectal cancer: a prospective study from the UK Biobank. J Transl Med. Sep 27 2023;21(1):669. doi:10.1186/s12967-023-04522-8 37759216
14 Maimaitiyiming M, Yang H, Zhou L, Zhang X, Cai Q, Wang Y. Associations between an obesity-related dietary pattern and incidence of overall and site-specific cancers: a prospective cohort study. BMC Med. Jul 10 2023;21(1):251. doi:10.1186/s12916-023-02955-y 37424008
15 Moazzen S, Cortes-Ibanez FO, van der Vegt B, Alizadeh BZ, de Bock GH. Diet quality indices and gastrointestinal cancer risk: results from the Lifelines study. Eur J Nutr. Feb 2022;61(1):317–327. doi:10.1007/s00394-021-02648-3 34338867
16 Neuhouser ML, Pettinger M, Tinker LF, . Associations of Biomarker-Calibrated Healthy Eating Index-2010 Scores with Chronic Disease Risk and Their Dependency on Energy Intake and Body Mass Index in Postmenopausal Women. J Nutr. Jan 14 2023;152(12):2808–2817. doi:10.1093/jn/nxac199 36040344
17 Nguyen S, Li H, Yu D, . Adherence to dietary recommendations and colorectal cancer risk: results from two prospective cohort studies. Int J Epidemiol. Feb 1 2020;49(1):270–280. doi:10.1093/ije/dyz118 31203367
18 Petermann-Rocha F, Ho FK, Foster H, . Nonlinear Associations Between Cumulative Dietary Risk Factors and Cardiovascular Diseases, Cancer, and All-Cause Mortality: A Prospective Cohort Study From UK Biobank. Mayo Clin Proc. Sep 2021;96(9):2418–2431. doi:10.1016/j.mayocp.2021.01.036 34366141
19 Ren X, Yu C, Peng L, . Compliance with the EAT-Lancet diet and risk of colorectal cancer: a prospective cohort study in 98,415 American adults. Front Nutr. 2023;10:1264178. doi:10.3389/fnut.2023.1264178 37927505
20 Schulpen M, van den Brandt PA. Mediterranean diet adherence and risk of colorectal cancer: the prospective Netherlands Cohort Study. Eur J Epidemiol. Jan 2020;35(1):25–35. doi:10.1007/s10654-019-00549-8 31494792
21 Shang X, Liu J, Zhu Z, . Healthy dietary patterns and the risk of individual chronic diseases in community-dwelling adults. Nat Commun. Oct 23 2023;14(1):6704. doi:10.1038/s41467-023-42523-9 37872218
22 Thompson AS, Tresserra-Rimbau A, Karavasiloglou N, . Association of Healthful Plant-based Diet Adherence With Risk of Mortality and Major Chronic Diseases Among Adults in the UK. JAMA Netw Open. Mar 1 2023;6(3):e234714. doi:10.1001/jamanetworkopen.2023.4714 36976560
23 Wang F, Ugai T, Haruki K, . Healthy and unhealthy plant-based diets in relation to the incidence of colorectal cancer overall and by molecular subtypes. Clin Transl Med. Aug 2022;12(8):e893. doi:10.1002/ctm2.893 35998061
24 Wang L, Du M, Wang K, . Association of ultra-processed food consumption with colorectal cancer risk among men and women: results from three prospective US cohort studies. BMJ. Aug 31 2022;378:e068921. doi:10.1136/bmj-2021-068921 38752573
25 Wang P, Song M, Eliassen AH, Wang M, Giovannucci EL. Dietary patterns and risk of colorectal cancer: a comparative analysis. Int J Epidemiol. Feb 8 2023;52(1):96–106. doi:10.1093/ije/dyac230 36515537
26 Willemsen RF, McNeil J, Heer E, Johnson ST, Friedenreich CM, Brenner DR. Dietary patterns with combined and site-specific cancer incidence in Alberta’s Tomorrow Project cohort. Eur J Clin Nutr. Mar 2022;76(3):360–372. doi:10.1038/s41430-021-00958-7 34168294
27 Xiao Y, Wang Y, Gu H, . Adherence to the Paleolithic diet and Paleolithic-like lifestyle reduce the risk of colorectal cancer in the United States: a prospective cohort study. J Transl Med. Jul 19 2023;21(1):482. doi:10.1186/s12967-023-04352-8 37468920
28 Yue Y, Hur J, Cao Y, . Prospective evaluation of dietary and lifestyle pattern indices with risk of colorectal cancer in a cohort of younger women. Ann Oncol. Jun 2021;32(6):778–786. doi:10.1016/j.annonc.2021.03.200 33812017
29 Zhang J, Nyvang D, Ibsen DB, . Adherence to the Danish food-based dietary guidelines and risk of colorectal cancer: a cohort study. Br J Cancer. Dec 2021;125(12):1726–1733. doi:10.1038/s41416-021-01556-x 34593992