# Results

## Literature search and screening results

Articles included in this systematic review were identified from literature searches conducted to identify all potentially relevant articles for the systematic review assessing the relationship between dietary patterns consumed and colorectal cancer^*^. The literature search (Appendix 4) yielded 1,436 search results after the removal of duplicates (see Figure 2). Dual-screening resulted in the exclusion of 982 titles, 360 abstracts, and 65 full-texts articles. Reasons for full-text exclusion are in Appendix 5. No additional articles were identified from the manual search. The body of evidence for colorectal cancer includes 29 articles^1–29^ published since 2020. In addition, this review updates an existing review,^†^ which developed and graded a conclusion based on 46 articles.

* Hoelscher DM, Anderson CAM, Booth S, . Dietary Patterns and Risk of Colorectal Cancer: A Systematic Review. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review; 2025.

† Boushey C, Ard J, Bazzano L, Heymsfield S, Mayer-Davis E, Sabaté J, Snetselaar L, Van Horn L, Schneeman B, English LK, Bates M, Callahan E, Butera G, Terry N, Obbagy J. Dietary Patterns and Breast, Colorectal, Lung, and Prostate Cancer: A Systematic Review. July 2020. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: 10.52570/NESR.DGAC2020.SR0104

Figure 2 Literature search and screen flowchart

Literature search and screen flowchart The literature searches in PubMed, Embase, and Cochrane, retrieved 3,305 records after removing duplicates. 0 were found through manual search methods. 982 titles, 360 abstracts, and 65 full-texts were excluded. 29 articles were included in the systematic review.

## Adults and older adults

The 2025 Dietary Guidelines Advisory Committee updated the existing systematic review by synthesizing the additional 29 articles that were published between January 2020 and January 2024 and met inclusion criteria, and assessing how this new evidence relates to the conclusion statement from the existing review.

### Description of the evidence

Twenty-nine articles met inclusion criteria examining the relationship between dietary patterns consumed and risk of colorectal cancer (Table 6).^1–29^ Twenty-seven articles analyzed data from prospective cohorts^1,3–19,21–29^ and 2 articles analyzed case-cohort data.^2,6,20^

#### Population

Analytic sample size ranged from N=1,189^12^ up to N=422,702.^18^ Follow-up durations ranged between a median of 6 years up to 28 years.^24^ Four articles combining data from the Nurses’ Health Study and the Health Professional Follow-up Study did not report follow-up duration, but is estimated to be about 30y based on information from other articles reporting on this cohort.^1,11,12,23^

The number of cases identified across the studies varied and ranged from 197 colorectal cases from a cohort of 9,886^7^ to 18,768 colorectal cases from a cohort of 112,468 participants.^9^

Articles used data collected from a total of 8 countries with 13 articles using data collected in the United States:

- Nurses’ Health Study and Health Professionals Follow-up Study (HPFS)^1,11,12,23–25^, n=6
- NHS II,^28^ n=1
- Prostate, Lung, Colorectal, and Ovarian (PLCO) Cancer Screening Trial,^19,27^ n=2
- Women’s Health Initiative (WHI),^7,16^ n=2
- Multi-Ethnic cohort,^10^ n=1
- WHI-Dietary Modification trial,^9^ n=1

Additional countries and cohorts were represented in the data as follows:

- United Kingdom, n=7 (UK Biobank,^6,8,13,14,18,21,22^ n=7)
- Canada, n=2 (Alberta’s Tomorrow Project,^26^ n=1; Canadian Study of Diet, Lifestyle and Health (CSDLH),^2^ n=1)
- Spain, n=2 (PREvencion con DIeta MEDiterranea (PREDIMED),^3^ n=1; European Prospective Investigation into Cancer and Nutrition (EPIC)-Spain,^4^ n=1)
- China, n=1 (Shanghai Women’s Health Study (SWHS); Shanghai Men’s Health Study (SMHS),^17^ n=1)
- Denmark, n=1 (Danish Diet, Cancer and Health cohort (DCH),^29^ n=1)
- France, n=1 (NutriNet-Santé,^5^ n=1)
- The Netherlands, n=2 (The Netherlands Cohort Study,^20^ n=1; Lifelines,^15^ n=1)

##### Health status

Most studies reported mean BMI ≥25.0 kg/m2 of study participants,^3,4,6–10,13–18,22,24,26–29^ but the full range included 23.8 kg/m2^5^ up to 31.1kg/m2.^7^. Many studies also reported that >40% of the populations had overweight or obesity.^6–9,12,13,17,18,22,26,29^ Among studies that reported information on smoking (n= 19), ever smoking ranged from 24%^11^ to 69%;^10^ in the 6 articles that reported current smoking, there was a range from 4^21,23^ to 26%.^24^ Only 5 articles reported family history of cancer or colorectal cancer (family history of cancer 37%^6^ and 49%^3^) and family history of colorectal cancer ranged from 5%^20^ to 19%^1^ in the 3 articles that reported it).

##### Race and/or Ethnicity

The reported race and/or ethnicity of study samples indicated homogeneity across the included articles. Nineteen articles included populations that were >77% White.^1,2,6,8,9,11–14,16,18,19,21–25,27,28^ Three included articles reported that <40% of the study population was White, one of which was 100% Chinese ancestry;^17^ one was 100% Black;^7^ and the other reported 13-19% “African-American”, 7% “Native Hawaiian”, 28-30% “Japanese American”; 21-24% “Latino”, with about 25-26% “White”.^10^ Seven of the articles did not report the race or ethnicity of their populations,^3–5,15,20,26,29^ and were conducted in the following populations: Dutch,^15,20^ Spanish,^3^, Canadian,^26^ or Danish.^29^.

##### Socioeconomic position (SEP)

Variability in participants’ SEP was demonstrated among the articles reporting such information. Nine articles did not report an indication of socioeconomic position,^1,10–12,19,23–25,28^ however, 7 of those articles used data from populations of 100% health professionals.^1,11,12,23–25,28^ Education was the most commonly-reported indicator of socioeconomic position, but income, socioeconomic status (e.g. Townsend index), occupation status, and/or cohabitation status were also reported. Populations with high education or employment status were represented in 10 articles,^1,2,11,12,14,16,23–25,28^ low education or household income in 3 articles,^3,4,8^ or mixed socioeconomic position in 14 articles represented by household income, education, occupation, or Townsend index.^5–7,9,13,15,17,18,20–22,26,27,29^

#### Intervention/Exposure and Comparator

Dietary patterns consumption was examined among participants whose mean ages ranged from 44 years^5^ to 65.5 years^16^. The majority of articles assessed dietary intake multiple times throughout the course of study,^1–3,5–9,11–14,16,18,21–25,28^ however ,12 of those only used a single measure in their analysis.^2,3,7,9,11,13,16,18,22–25^ Nine articles only collected and used dietary data from a single collection at baseline.^4,10,15,17,19,20,26,27,29^ Therefore, the majority of analyses were based on a single measure of dietary intake. The most common diet assessment method used was FFQ (n=21),^1–3,7,9–12,15–17,19–21,23–29^ followed by 24-hour dietary recall (n=7),^5,6,8,13,14,18,22^ and diet history questionnaires (n=1).^4^

Dietary pattern methods included:

- Index/Score analysis: n=25^2,3,5–13,15–25,27–29^
- Factor/Cluster: n=3^1,4,26^
- Reduced Rank Regression: n=2^14,26^

A visualization of all dietary pattern components in each dietary pattern examined in relation to outcomes of interest is available in Appendix 6.

#### Outcomes

Methods used to assess incident cases of colorectal cancer varied across the articles. Thirteen articles initially identified cases using self-report, then confirmed cases using the national death index, medical records or pathology reports, health insurance and mortality registries.^1,5,7,9,11,12,16,19,23–25,27,28^ The remaining articles determined incident cases using linkages to cancer, death, or health registries, medical or hospital records, national health services^2–4,6,10,13,15,17,18,20–22,26,29^, or did not report their methods.^8,14^

All but one of the included articles reported risk of overall colorectal cancer,^1–25,27–29^ and many studies also reported risk of colon cancer (n=9)^2,6,8,9,11,17,20,26,29^ and risk of rectal cancer (n=13).^2,4,6,8,10,11,13,17,19,20,24,28,29^

### Synthesis of the evidence

Across the body of evidence, reported results supported two general directions of results, regardless of statistical significance, and with minor variation in magnitude of effect estimates. In 21 articles,^2–5,8–11,13,15–17,19,21–23,25–29^ dietary patterns related to lower risk of colorectal cancer were generally characterized by higher intakes of: vegetables, fruits, legumes and nuts, whole grains, fish, unsaturated fats; and lower intakes of: red and processed meats, refined grains, sugar-sweetened foods and beverages. In 15 articles^1,4,7,9,11–14,18,22–26,28^ dietary patterns related to higher risk of colorectal cancer were generally characterized by higher intakes of: red and processed meats, fried potatoes, refined grains, sugar-sweetened foods and beverages; and lower intakes of vegetables, fruit, legumes and nuts, whole grains, tea and coffee.

When synthesized together and oriented as evidence for a relationship with lower risk of colorectal cancer, the patterns shared similar direction of findings and magnitude of effect estimates in 66 comparisons from 27 articles and were generally characterized by higher intakes of vegetables, fruits, legumes and nuts, whole grains, and lower intakes of red and processed meats, refined grains, fried potatoes, saturated fat, and sugar-sweetened foods and beverages. Some of these dietary patterns also included fish, low-fat dairy, tea and coffee. While half of the dietary pattern comparisons from 12 of those articles reported results that were not statistically significant, they were consistent in direction and dietary pattern components and supported the overall findings described above.^3,4,7,11,15–17,21,22,25,26,28^

A subset of articles reported results between dietary patterns and colon cancer (n=9)^2,6,8,9,11,17,20,26,29^ and rectal cancers (n=13)^2,4,6,8,10,11,13,17,19,20,24,28,29^ separately. While results for these sub-categories were typically less statistically significant, less consistent in direction across quartiles, and had wider confidence intervals, results tended to be in the same direction as overall results.

Most of these dietary patterns included fish as a contributor to these dietary patterns, and while it was included as a positive component in many patterns associated with lower risk of colorectal cancer, it was also included as a positive component in many patterns that were associated with higher risk of colorectal cancer. Dairy and/or milk products were often included but considered differently across these dietary patterns, such as with total dairy and/or milk products scored as a negative component compared to specifically scoring low-fat dairy positively. Tea and/or coffee was included as a positive component in many of the comparisons of the same dietary patterns, but it was unclear how much they were contributing to the overall relationship. The methods and labels for these dietary patterns varied across the body of evidence, including a priori indices or scores as well as posteriori or hybrid methods (e.g., factor analysis and reduced rank regression) across observational studies.

Dietary patterns derived from various indices/scores were used in the majority articles, which reported similar results despite variation in the name, label, or style of dietary pattern (e.g., Mediterranean, dietary guideline-related, “Plant-based”, or other).

- Dietary Guidelines-related scores (e.g., Healthy Eating Index) were examined in 8 articles^2,3,7,9,16,17,21,25^ and associated with a statistically significant lower risk of colorectal cancer in 2 articles.^2,9^ While results were not statistically significant, 5 out of 8 articles reported results in a consistent direction of an inverse relationship between Dietary Guidelines-related scores and colorectal cancer. These articles generally scored the following dietary pattern components positively: vegetables (not potatoes, French fries), fruit, legumes and nuts, whole grains; and negatively: added sugars/sugar-sweetened beverages, red and processed meats.
- Country-specific dietary patterns scores were examined in 3 articles, including adherence to the Dutch Dietary Guidelines (n=2),^15,29^ and to the Programme National Nutrition Santé Guidelines Score in France (n=1).^5^. Adherence to these county-specific dietary pattern scores were associated with lower risk of colorectal cancer in 2 of the 3 articles,^5,29^ while the other reported a result in the same direction, however it was not statistically significant.^15^. These scores generally scored the following positively: vegetables, fruit, legumes, whole grains; and negatively: meats (all, red, and/or processed).
- Plant-based dietary patterns were assessed in 8 articles including the Plant-Based Diet Index (PDI),^10,11,13,25,28^ PDI healthful (hPDI),^11,13,21–23,25,28^ PDI unhealthful (uPDI)^11,13,22,23,25,28^ and modifications.
  ○ Two of 5 analyses reported an association with a PDI or modified PDI pattern and lower risk of colorectal cancer,^10,13^ while 1 other reported a non-significant result in the same direction.^25^ The other 2 analyses reported no relationship between PDI or modified PDI pattern and colorectal cancer.^11,28^ PDI patterns generally shared the following components: positively coded: vegetables; fruits; nuts; legumes; whole grains; vegetable oils; tea and coffee; fruit juices; sugar-sweetened beverages; refined grains; potatoes; sweets/desserts; negative: animal fats; dairy; eggs, fish/seafood; meat (poultry and red meat); miscellaneous animal-based foods.
  ○ Three of 8 analyses reported an association with a healthful PDI pattern and lower risk of colorectal cancer,^13,21,23^ with the 5 other analyses reported a non-significant result in the same general direction.^10,11,22,25,28^ Healthful PDI patterns generally shared the following components: positively coded: vegetables; fruits; nuts; legumes; whole grains; vegetable oils; tea and coffee; negative: fruit juices; sugar-sweetened beverages; refined grains; potatoes; sweets/desserts; animal fats; dairy; eggs, fish/seafood; meat (poultry and red meat); miscellaneous animal-based foods.
  ○ Three of 7 analyses reported an association with an unhealthful PDI pattern and higher risk of colorectal cancer,^11,13,23^ while 2 others reported non-significant associations in the same direction.^22,25^ Unhealthful PDI: positively coded: fruit juices; sugar-sweetened beverages; refined grains; potatoes; sweets/desserts; negative: whole grains; fruits; vegetables; nuts; legumes; vegetable oils; tea and coffee; animal fats; dairy; eggs, fish/seafood; meat (poultry and red meat); miscellaneous animal-based foods.
- Five articles assessed empirical dietary index for hyperinsulinemia (EDIH) or empirical dietary inflammatory pattern (EDIP).^9,12,21,25,28^ Seven out of 8 analyses reported an association with the EDIH or EDIP pattern and higher risk of colorectal cancer.^9,12,25,28^ The other analyses report no association between an EDIP pattern and colorectal cancer.^21^
  ○ EDIH pattern generally shared the following components positively scored: red meat; processed meat; poultry; tomatoes; french fries, fish (non-dark); low-fat dairy; eggs; high-energy beverages (cola and other carbonated beverages with sugar, fruit drinks); low-energy beverages; margarine; cream soups; negative: green leafy vegetables; whole fruit; high-fat dairy products; coffee; wine.
  ○ EDIP pattern generally shared the following components and is reverse coded: positively scored (anti-inflammatory): vegetables (dark yellow: carrots, or squash), vegetables (leafy green: cabbage, spinach, lettuce); fruit juice (apple, cantaloupe, orange, or other fruit juice); pizza; snacks (cracker, potato chips); tea; coffee. negatively scored (pro-inflammatory): vegetables, other: mixed, green pepper, cooked mushroom, eggplant, zucchini, or cucumber); processed meat (sausage); red meat (beef, or lamb); organ meat (beef, calf, or chicken liver), fish, canned tuna; refined grains (white bread, biscuit, white rice, pasta, or vermicelli); high- and low-energy beverages (cola with sugar, carbonated beverages with sugar, fruit punch drinks); tomatoes.
- Cancer specific dietary patterns were assessed in 4 articles including WCFR/AICR scores,^8,15,20,25^ American Cancer Society Index,^15^ and a colorectal cancer dietary score.^25^ Two articles reported an inverse association between cancer specific dietary patterns and risk of colorectal cancer.^8,15^ Two articles reported non-significant results that were generally in a similar direction.^15,25^ A case-cohort analysis reported no association between WCFR/AICR score and colorectal cancer. Dietary patterns generally shared the following components positively scored: vegetables; fruit; whole grains; dietary fiber; negative: red and processed meat; sugar sweetened beverages; alcohol; sodium; energy-dense foods
- “Mediterranean” dietary pattern scores were assessed in 4 articles and no clear direction of effect was reported with risk of colorectal cancer.^4,20,21,25^ Three articles reported results in an inverse direction with mediterranean dietary pattern scores and lower risk of colorectal cancer, but were not statistically significant.^4,21,25^ Dietary patterns shared the following components positively scored: vegetables (not potatoes), fruit, legumes, nuts, fish, and unsaturated vegetable oils/fats; positive in moderation: alcoholic beverages; and negatively scored: red and processed meat, sugar-sweetened beverages.
- ‘DASH’ style scores were examined in 2 articles^17,25^ in which 1 article reported a statistically significant association with a lower risk of colorectal cancer.^17^ The other article was not significant, but reported consistent results in an inverse direction.^25^ “DASH”-style indices that similarly scored the following components positively: vegetables (not potatoes and legumes); nuts and legumes; fruit and fruit juice; whole grains; low-fat dairy; and negatively: red and processed meat; sugar-sweetened beverages; sodium. The study that reported significant associations with colorectal cancer modified the DASH dietary pattern by removing whole grains, and sugar-sweetened beverages and included all Dairy comparted to only low-fat.^17^
- Patterns focused on ultra-processed foods using the Nova classification were reported in 2 articles with mixed results.^6,24^ One article reported a positive association between a dietary pattern with higher Nova classification with higher risk of colorectal cancer,^24^ while the other article reported no association.^6^
- Other index/score analyses were examined in 7 articles including the Global Diet Quality Score or Prime Diet Quality Score (healthy and unhealthy),^25,28^ Lifelines Diet score,^15^ Chinese Food Pagoda (CHFP),^17^ Paleolithic Diet Score,^27^ Dietary Risk Score,^18^ and EAT-Lancet Reference Diet.^19^ Out of 9 analyses, 3 reported an association between these other patterns and lower risk of colorectal cancer.^17,19,27^ The remaining analyses reported no significant associations, however 5 were in a similar direction.^15,19,25,28^. Generally, these scores commonly scored the following components positively: vegetables, fruit, legumes, nuts and seeds, whole grains, fish and shellfish; poultry and game; low-fat dairy; eggs; oils (liquid). negative: meat; refined grains; sweets; sugar-sweetened beverages and juice; purchased deep fried foods; neutral (moderate): high-fat dairy; red meat. One article reported results in the opposite direction that the Dietary Risk Score was associated with a higher risk of colorectal cancer.^18^ This was expected as it positively scored: red meat; processed meat; whole-milk; spread (butter, other/ margarine, and/or flora pro-active/benecol); salt added to food; negative: vegetables and fruit; cereals; total fish; water.

Dietary patterns examined by factor/cluster analysis or reduced-rank regression were examined in 4 articles.^26^ Though patterns varied, dietary patterns higher in the following components (unprocessed red meat; processed meat; and high fat dairy food; refined grains; and sweets) were associated with higher risk of colorectal cancer in 3 articles^4,25,26^. Dietary patterns commonly higher in vegetables, fruits, and whole grains tended to be associated with a lower risk of colorectal cancer in 3 articles, but results were not statistically significant. The other remaining factor/cluster analysis or reduced-rank regression analyses had mixed results.^4,14,26^

### Conclusion statement and grade

The 2025 Dietary Guidelines Advisory Committee updated the existing conclusion statement^*^,^†^ (Appendix 2) to answer the question, “What is the relationship between dietary patterns consumed and risk of colorectal cancer?” based on their review of the body of evidence on adults and older adults from an additional 29 articles that met inclusion criteria and were published between January 2020 and January 2024 (Table 5).

* A conclusion statement is carefully constructed, based on the evidence reviewed, to answer the systematic review question. A conclusion statement does not draw implications and should not be interpreted as dietary guidance.

† Boushey C, Ard J, Bazzano L, Heymsfield S, Mayer-Davis E, Sabaté J, Snetselaar L, Van Horn L, Schneeman B, English LK, Bates M, Callahan E, Butera G, Terry N, Obbagy J. Dietary Patterns and Breast, Colorectal, Lung, and Prostate Cancer: A Systematic Review. July 2020. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: 10.52570/NESR.DGAC2020.SR0104

Table 5 Conclusion statement, grades for dietary patterns consumed by adults and older adults and risk of colorectal cancer

Conclusion Statement | Dietary patterns consumed by adults and older adults that are characterized by higher intakes of vegetables, fruits, legumes and nuts, and whole grains, and lower intakes of red and processed meats, refined grains, fried potatoes, saturated fat, and sugar-sweetened foods and beverages are associated with lower risk of colon and rectal cancer. Some of these dietary patterns also included fish, low-fat dairy, tea and coffee. This conclusion statement is based on evidence graded as moderate.
Grade | Moderate
Body of Evidence | 29 included articles (27 PCS, 2 case-cohort studies) assessed as they relate to the evidence in the existing review^†^ (46 articles)
Consistency | A few concerns with variability with the magnitude of results and minimal concerns with variability in the direction of results.
Precision | Some concerns with studies reporting wider confidence intervals across effect estimates.
Risk of bias | Some concerns with higher risk of bias, primarily due to confounding, the exposure only being measured one time, and the selection of the reported results.
Directness | A few concerns with exposure, comparators, and outcomes being examined that were directly related to the systematic review question.
Generalizability | Some concerns with generalizability to the U.S. population due to lack of diversity in race and/or ethnicity.

#### Assessment of the evidence

The body of evidence underlying the conclusion statement includes 29 articles published since 2020, assessed as they relate to the evidence included in the existing review.^†^ Dietary patterns were assessed using various analytic approaches, including an investigator-assigned dietary intervention, index/score analysis, factor/cluster analysis, and reduced rank regression. Incident cases of colorectal cancer was determined from various methods including self-report, registry linkage, medical and hospital records, death records or indices, and insurance databases. As outlined and described below, the body of evidence was assessed for the following elements used when grading the strength of evidence. This body of evidence includes both large and small studies (with significant as well as null findings) so publication bias may be less likely.

##### Consistency

The findings were consistent in direction and magnitude of findings when oriented towards a lower risk of colorectal cancer. Twenty-one of 29 articles reported (15 statistically significant) associations between dietary patterns and lower risk of colorectal cancer. Fifteen of 29 articles reported (11 statistically significant) associations between dietary patterns and higher risk of colorectal cancer. When synthesized together lower risk of colorectal cancer was associated with patterns characterized by higher intakes of vegetables, fruits, legumes and nuts, whole grains, and lower intakes of red and processed meats, refined grains, fried potatoes, saturated fat, and sugar-sweetened foods and beverages. Within the 16 articles that reported only non-significant results, 12 articles reported results consistent in direction and food components as the significant results. Results for subcategories of risk of colon and rectal cancer subtypes were typically less significant and had greater heterogeneity, however, results tended to be in the same direction as overall results.

##### Precision

There were some concerns that the width of confident intervals varied across studies, with moderate to large variances. There was a total of 29 observational studies and the majority had large analytic sample sizes with a sufficient number of colorectal cancer cases

##### Risk of bias

There were numerous risks of bias across domains, which may influence the reported results (Table 7). Many of the studies did not account for colorectal cancer screening which was identified as a key confounder a priori. Many of the articles also may be at a higher risk of exposure classification due to only assessing dietary patterns at one time point and not accounting for potential diet changes over long periods of follow-up, or measuring habitual consumption using tools that more accurately measure acute dietary intake. Additionally, because many of the studies were observational, they didn’t have pre-specified analytic plans and therefore tended to be at higher risk of bias for selection of reported results.

##### Directness

Studies and/or analyses were designed to directly examine the relationship between dietary patterns and risk of colorectal cancer outcomes.

##### Generalizability

Socioeconomic positions of participants varied across included articles and were likely generalizable to the U.S. population. The United States was the most represented country among the included articles (n= 13), however, there were some concerns with the generalizability of the racial and ethnic representation. The majority of participants across articles were White with less representation from diverse racial and/or ethnic groups which led to concerns with applicability to the U.S. population. Participants across the body of evidence represented a range of health disparities based on studies that reported such information, including a majority of participants without chronic disease as well as those with overweight, obesity, and variable family history of cancer. Outcomes examined in the body of evidence, including overall risk of colorectal cancer, colon cancer, and rectal cancer are relevant to the U.S. population of interest.

## Research recommendations

- Examine populations that are generalizable to the U.S. population with regards to socioeconomic position and racial and/or ethnic groups.
- Adopt methodologic approaches for defining different dietary patterns such that patterns can be consistently identified, scored and compared across studies, including clearer description of foods and food components (e.g. low-fat dairy vs. dairy, red and processed meat vs total protein).
- Establish population studies starting earlier in life to better capture dietary patterns contributing to risk of colorectal cancer risk later in life.
- Assess associations of dietary patterns by sub-types of colorectal cancer defined by location within the colon, cancer genetics and other histopathologic characteristics.
- Collect and include information on the confounding contribution of colorectal cancer screening when assessing the relationship between dietary patterns and colorectal cancer.

Table 6 Evidence examining the relationship between dietary patterns consumed by adults and older adults and risk of colorectal cancer^a^

Article Information | Intervention/exposure and comparator | Results | Methodological considerations
Arima, 2022^1^; United States; NHS; HPFS; Analytic N=134775; NHS: 87326; HPFS: 47449; Participant characteristics:; - [underlined: Health]: BMI, mean kg/m2: 25.3-26.3 (HPFS), 24.9-25.9 (NHS); - Family Hx CRC: 15-19%; - Smoking, pack-years mean: 9-15.2; - Postmenopausal ~73-75% (NHS); - [underlined: Race and/or Ethnicity]: Predominantly Non-Hispanic White; - [underlined: SEP]: NR; 100% health professionals; [underlined: Selection:] Excluded those who had or with: Hx of Cx; Missing DP data; Implausible TEI; Hx of colitis | DP Age(s): 63 to 65y, mean HPFS; 60 to 63y, mean NHS (range: 30 to 75y at baseline); DP(s) examined: “Western”; DP Components:; - “Western”: Higher loadings (coefficients >0.30) for: Potatoes; French Fries; Refined grains; Unprocessed red meat; Processed meat; Eggs; High fat dairy food; Desserts (cake, chocolate, candy bars; cookies; brownies, pie, pastries); Sugar-sweetened beverages; Condiments (soy sauce, red chili sauce, pepper, nondairy creamer, Worcestershire sauce); Butter; Mayonnaise; Margarine; Snacks (chips, popcorn, crackers); Pizza; Creamy soups; - Top 3 loadings >0.50 were Unprocessed red meat; Processed meat; and High fat dairy food; - T3 vs. T1 intakes were higher in Unprocessed red meat; Processed meat; Alcohol (only HPFS); Similar in Vegetables; Fruit; Poultry [IDairy intakes NR]; DP Method(s): Factor/Cluster; Analysis: PCA; Comparisons: Categorical, tertiles of “Western” DP with T1, HR: 1 REF | Follow-Up Duration: NR, ~ 30y; Results for Overall CRC:; “Western” DP & Incident CRC, T1, HR: 1 REF; T2, HR: 0.98, 95 % CI: 0.88, 1.09; T3, HR: 1.14, 95 %CI: 1.01, 1.29; p-trend=0.01; Summary: Positive: “Western” DP & CRC | - Did not account for: Race/Ethnicity, SEP, TEI; - Diet assessment: FFQ every 4y; - Outcome measurement: Incident cases determined by self-report, NDI; Tumor location and Dz stage from medical records & study physician; Both colon and rectal carcinomas included based on colorectal continuum model;; - n=3200 incident CRC cases; Secondary analysis by bacteria status reported in subset of n=1175 cases; - Funding: NIH; American Association for Cancer Research (Stand Up 2 Cancer Partner); Project P Fund, The Friends of the Dana-Farber Cancer Institute, Bennett Family Fund, and the Entertainment Industry Foundation through the National Colorectal Cancer Research Alliance
Arthur, 2023^2^; Canada; Canadian Study of Diet, Lifestyle and Health (CSDLH); Analytic N=5594; 573 cases, 5021 subcohort members (2225 men, 2796 women).; Participant characteristics:; - [underlined: Health]: BMI, mean kg/m2: 25.1 cases; 24.4 subcohort; - Current smoker: 6% cases and 6% subcohort; - [underlined: Race and/or Ethnicity]: ~97% White; - [underlined: SEP]: Education: ~40% graduate school; - [underlined: Selection:] Excluded those who had or with: Hx of Cx; Unusual TEI; Included primarily university alumni (small amount from Cancadian Cancer Society).; Sensitivity analysis excluded first 2y; FU: attenuated results but still SS. | DP Age(s): ~65y, mean at baseline (65.1 cases; 65.4y subcohort); DP(s) examined: Healthy Eating Index (HEI-2015) [Krebs-Smith 2018]; DP Components:; - HEI-2015: Positive: Total Vegetables; Greens and Beans; Total Fruit; Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; PUFA+MUFA/SFA. Negative: Refined Grains; Added Sugars; SFA; Sodium; DP Method(s): Index/Score Analysis; Comparisons: Categorical, quintiles of HEI with Q1, HR: 1 REF | Follow-Up Duration: 7 y (cases) to 13y (subcohort), median (IQRs: 4 to 16); Results for Overall CRC:; HEI-2015 & CRC, HR (95% CI), Q1, HR: 1 as REF; ♀+♂, Overall; Q2, 0.75 (0.58, 0.97); Q3, 0.92 (0.72, 1.18); Q4, 0.96 (0.75, 1.23); Q5, 0.65 (0.49, 0.85); P-trend=0.056; Sex-stratified results; Overall; ♂Q2, 0.73 (0.51, 1.04); ♂Q3, 0.74 (0.52, 1.04); ♂Q4, 0.99 (0.71, 1.37); ♂Q5, 0.56 (0.38, 0.81); P-trend: 0.041; ♀Q2, 0.86 (0.57, 1.29); ♀Q3, 1.22 (0.82, 1.81); ♀Q4, 1.07 (0.72, 1.59); ♀Q5, 0.88 (0.58, 1.34); P-trend: 0.902; P-intx: 0.029; Summary: Inverse: HEI-2015 & overall CRC; Colon; Distal Colon;; NS/Inverse: HEI & Proximal colon; Rectum; Interaction with sex: HEI-2015 & overall CRC; Colon; | - Did not account for: Race/Ethnicity (97% White), Screening; - Diet assessment: FFQ at baseline (verified sub-set that completed additional FFQ and 24-h recall); - Outcome measurement: Incident cases determined by record linkage to the Canadian Cancer Registry (CCR) and to the Ontario Cancer Registry; - Funding: NR
Barrubés, 2020^3^; Spain; PREvencion con DIeta MEDiterranea (PREDIMED); Analytic N=7216; Participant characteristics:; - [underlined: Health]: BMI, mean: 29.7; 100% high-CMR;; - 83% HTN; 49% DM; Smokers: 62% never, 25% former, 14% current; 49% Family Hx of Cx; 22% Aspirin users; 3% HRT (♀); - [underlined: Race and/or Ethnicity]: NR (Spanish); - [underlined: SEP]: Education: 7% university+; 93% high school or less; - [underlined: Selection:] Excluded those with or who had: severe Chronic Dz; malignant tumor Dz in last 5y; alcohol or drug abuse, allergy to nuts/olive oil; BMI=40+; implausible/extreme TEI; incomplete or missing FFQ at baseline; Selected those at high risk of CVD. | DP Age(s): 67y, median (IQR: 62-72); range: 55 to 80y; DP(s) examined: Alternative HEI (AHEI)-2010 [Chiuve, 2012]; DP Components:; - AHEI-2010: Positive: Vegetables (not potatoes); Fruit; Legumes and Nuts; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA. Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Trans FA; Sodium. Neutral: Alcohol; DP Method(s): Index/Score Analysis; Comparisons: Continuous, AHEI-2010 score | Follow-Up Duration: 6.0y, median; Results for Overall CRC:; AHEI-2010 & CRC, HR: 0.81, 95% CI: 0.52, 1.27; p=0.362; Summary: NS/Inverse: AHEI-2010 & CRC | - Did not account for: Race/ethnicity (Spanish); Screening; - Diet assessment: FFQ at baseline (verified sub-set from RCT); - Outcome measurement: Incident cases/events defined by ICD and based on first invasive CRC, histological exam to confirm, and events from medical records and NDI (reviewed by blinded physicians/researchers); - Funding: Spanish Instituto de Salud Carlos III (ISCIII)/CIBEROBN (the Centro de Investigac on Biomedica en Red de Fisiopatologıa de la Obesidad y Nutricion), which are funded by FEDER/Spanish Government; Centro Nacional de Investigaciones Cardiovasculares (CNIC); Fondo de Investigaciones Sanitarias; Ministerio de Ciencia e Innovacion; Autonomous Govt. of Catalonia; Navarra Regional Govt.; Fundacion Patrimonio Comunal Olivarero, California Walnut Commission, Borges SA, and Morella Nuts
Castelló, 2022^4^; Spain; European Prospective Investigation into Cancer and Nutrition (EPIC)-Spain; Analytic N=40898; Participant characteristics:; - [underlined: Health]: BMI, mean: ~27.4-28.2;; - Smokers: 47-65% never; - [underlined: Race and/or Ethnicity]: NR; - [underlined: SEP]: Education: majority < secondary/high-school (30-40% none, 37-41% primary, 12-17% secondary, 8-16% univesity+); [underlined: Selection:] Excluded those with or who had: BMI of 60+; implausible/extreme TEI; first y of F/U; males | DP Age(s): 46 to 51y (median) at entry (range: 29 to 69y); DP(s) examined: “Western” DP; “Prudent” DP; “Mediterranean” DP; DP Components:; - “Western” DP: high intakes of high-fat dairy products, processed meat, refined grains, sweets, caloric drinks, convenience food and sauces [e.g., crackers, snacks, egg derivatives; processed white/blue fish]; Low intakes of low-fat dairy products and whole grains;; - “Prudent” DP: high intakes of low-fat dairy products, vegetables, fruits, whole grains and [veg./fruit] juices; - “Mediterranean” DP: high intakes of fish, vegetables, legumes [Peas, lentils, chickpeas, beans and broad beans], boiled potatoes, fruits, olives, and vegetable oil; Low intake of [veg./fruit] juices; DP Method(s): Factor/Cluster; Analysis: PCA; Comparisons: Continuous (per-SD) of each DP (Western; Prudent; Med) and categorical by quartiles with Q1, HR: 1 REF | Follow-Up Duration: 16.98y, median (cases, 10.5y; deaths 11.1y); Results for Overall CRC:; Western DP & CRC, HR (95% CI); overall CRC, F/U > 1y; Q2, HR: 1.30 (1.02, 1.66); Q3, HR: 1.47 (1.16, 1.87); Q4, HR: 1.51 (1.18, 1.93); p-trend=0.001; per-SD, HR: 1.15 (1.05, 1.25); overall CRC in Y1-Y10 F/U; Q2, HR: 1.28 (0.85, 1.91); Q3, HR: 1.24 (0.81, 1.89); Q4, HR: 1.53 (0.99, 2.36); p-trend=0.087; per-SD, HR: 1.17 (0.99, 1.37); Prudent DP & CRC; overall CRC, F/U > 1y; Q2, HR: 0.84 (0.67, 1.06); Q3, HR: 0.79 (0.62, 1.00); Q4, HR: 0.83 (0.65, 1.05); p-trend=0.092; per-SD, HR: 0.92 (0.85, 1.01); overall CRC in Y1-Y10 F/U; Q2, HR: 0.58 (0.39, 0.86); Q3, HR: 0.73 (0.50, 1.07); Q4, HR: 0.85 (0.57, 1.25); p-trend=0.547; per-SD, HR: 0.94 (0.81, 1.09); Mediterranean DP & CRC; overall CRC, F/U > 1y; Q2, HR: 0.91 (0.71, 1.15); Q3, HR: 0.98 (0.77, 1.24); Q4, HR: 1.19 (0.94, 1.50); p-trend=0.107; per-SD, HR: 1.05 (0.96, 1.14); overall CRC in Y1-Y10 F/U; Q2, HR: 0.81 (0.55, 1.18); Q3, HR: 0.69 (0.46, 1.02); Q4, HR: 0.78 (0.52, 1.16); p-trend=0.165; per-SD, HR: 0.84 (0.73, 0.98); Summary: Positive: “Western” DP & overall CRC (F/U >1y; NS/Positive: F/U Y1-Y10); NS/Positive: Proximal; Distal; Rectum; NS/Inverse (no clear/consistent effects): “Prudent” DP & overall CRC (F/U >1y or Y1-Y10); Proximal; Distal; Rectum Inverse: Meditteranean DP & Distal CRC (♂); NS/Inverse (no clear/consistent effects):“Mediterranean” DP & overall CRC; Proximal; Rectum (F/U >1y or Y1-Y10) | - Did not account for: Race/Ethnicity, Screening; - Diet assessment: Diet Hx questionnaire; - Outcome measurement: Incident cases identified by cancer and registry linkage; definined by ICD via first occurrence of primary malignant tumor of colon (Proximal of splenic flexure: cecum, ascending, transverse; Distal: descending; sigmoid) or rectum (at recto sigmoid junction or rectum); Tumors with overlapping lesions or non-specified locations were excluded from sub-type analyses;; - n=568 cases CRC identified; - Funding: Alcala de Henares and Autonomous community of Madrid; International Agency for Research on Cancer (IARC); Department of Epidemiology and Biostatistics, School of Public Health, Imperial College London; Health Research Fund (FIS)—Instituto de Salud Carlos III (ISCIII), the Regional Governments of Andalucía, Asturias, Basque Country, Murcia and Navarra, and the Catalan Institute of Oncology—ICO (Spain)
Chaltiel, 2022^5^; France; NutriNet-Santé; Analytic N=75634; Participant characteristics:; - [underlined: Health]: BMI, mean: 23.8; - 24% HRT; - [underlined: Race and/or Ethnicity]: NR; - [underlined: SEP]: HH Income: 45% low, 27% low-mid, 28% mid, 28% high; - Education: 65% university, 34% secondary, 1% primary or less; - Cohabitation: 72% cohabitating; 28% living alone; - Most common occupation status: 24% managerial, 20% retired (<20% each: employees, intermediate profession, unemployed, student, famer/self-employed, manual worker); [underlined: Selection:] Excluded those with or who: were under-reporters; missing diet/covariate data; prevalent Cx | DP Age(s): 44y, mean (SD: 14.6); DP(s) examined: Programme National Nutrition Santé Guidelines Score (PNNS-GS2); DP Components:; - PNNS-GS2, Positive: Vegetables and Fruit; Fish and Seafood; Vegetable Fat. Negative: Sweetened Foods; Soda (drink water); Added Fat; Salt. Neutral: Bread, Cereals, Potatoes, and Legumes; Meat and Poultry; Fatty Fish; Eggs; Milk and Dairy Products; Alcohol; DP Method(s): Index/Score Analysis; Comparisons: Continuous (per-1=pt and per-SD increment) and categorical by tertiles with T1, HR: 1 REF | Follow-Up Duration: 6.7y, median; Results for overall CRC:; PNNS-GS2 & CRC, HR (95% CI); T2, HR: 1.18 (0.82, 1.69); T3, HR: 0.66 (0.43, 1.01); per-1-pt, HR: 0.94 (0.89, 0.99); per-SD, HR: 0.82 (0.69, 0.98) P= 0.03; Summary: Inverse: PNNS-GS2 & CRCx | - Did not account for: Race/Ethnicity, Screening; - Diet assessment: 24-hr recalls, ≥3 in first 2y of F/U; - Outcome measurement: Incident cases identified by self-report then verified by physician with medical records and validated by panel and/or linkage with health insurance and mortality registries; Cx defined by ICD codes; - CRCx, n=56; BCx, n=239; - Funding: Ministère de la Santé, Santé Publique France, Institut National de la Santé et de la Recherche Médicale (INSERM), Institut national de recherche pour l’agriculture, l’alimentation et l’environnement (INRAe), Conservatoire National des Arts et Métiers (CNAM) and Université Sorbonne Paris Nord
Chang, 2023^6^; United Kingdom; UK BIOBANK; Analytic N=197426; Participant characteristics:; - [underlined: Health]: BMI, OW: 41%; Ob 21%; Normal, 37%;; - 4% CVD; 4% DM; 26% High-BP; Smokers: 57% never; 36% Family Hx of Cx; 37% HRT “ever” (♀); - [underlined: Race and/or Ethnicity]: 95% White, 0.5% Mixed; 1.4% South Asian; 1.2% Black; 1% Chinese or other; - [underlined: SEP]: Education: 43% university/college (13% A/AS; 25% O; 10% vocational; 8% not listed); [underlined: Selection:] Excluded those with or who: were pregnant/unsure, implausible/extreme TEI; <1 24-hr recall; pre-existing Cx | DP Age(s): 58y, mean (SD: 8) (40-69y at baseline); DP(s) examined: UPF, Nova Classification System Group 4 [Monteiro, 2019]; DP Components:; - UPF, Nova4 (Table 1, Q4 > Q1 intakes): Higher intakes of Processed Meat; Total Fat; Total Carbohydrates; Total Sodium; Lower intakes of Vegetables; Fruit; Red Meat; Alcohol; - UPF, Nova4 (Fig. 1 top sources): Carbonated drinks; Fruit-based drinks; Ready-to-eat/heat foods; Industrial-processed breads; Dairy-based drinks; Pastries, buns, cakes; Sausage and other reconstituted meat products; Other beverages; Industrial-processed desserts; Sauces and spreads; Biscuits; Breakfast cereals; Confectionary; Packaged salty snacks; Alcoholic drinks; Sweeteners; Meat alternatives; Lower in Tea, Coffee; Fruit, Vegetables; Fruit juice; Beer and Wine; Cheese; DP Method(s): Index/Score Analysis; Comparisons: Continuous (per-10% increment in UPF) and categorical by quartiles with Q1, HR: 1 REF | Follow-Up Duration: 9.8y, median; Results for overall CRC:; Nova 4 & CRC, HR (95% CI); per-10%, HR: 1.02 (0.97, 1.06); Q2, HR: 1.03 (0.89, 1.20); Q3, HR: 1.01 (0.86, 1.18); Q4, HR: 1.05 (0.89, 1.24); p-trend=0.59; Summary: NS/Null: Nova 4 & CRC, Colon, Rectum | - Did not account for: Screening; - Diet assessment: 24-hr recalls, web-based ( 1 to 6); - Outcome measurement: Incident cases identified by cancer and registry linkage; Cx defined by ICD codes; - n= 15921 Cx cases identified (BC: n=3030; CRC: n=1670, Color n=1091, rectum n=579); - Funding:
Chebet, 2020^7^; United States; Women’s Health Initiative, WHI; Analytic N=9886; Participant characteristics:; - [underlined: Health]: BMI, mean: 31.1; OW: ~60%, Ob: 24%; - Smokers: 50% never; - [underlined: Race and/or Ethnicity]: 100% Black; - [underlined: SEP]: HH Income: 86% ≤ $74,999/y; Education: 75% college (some or degree) or higher; - [underlined: Selection:] Excluded those with or who had: severe clinical conditions (incl. Cx); predicted short survival, males, non-Black, unknown BMI, implausible TEI; incomplete or missing data (diet, PA, SEP, smoking, F/U) | DP Age(s): 50 to 59y, ~40%;; 60 to 69y, ~43%;; 70 to 79y, ~16%; DP(s) examined: Healthy Eating Index (HEI-2015) [Krebs-Smith 2018]; DP Components:; - HEI-2015: Positive: Total Vegetables; Greens and Beans; Total Fruit; Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; PUFA+MUFA/SFA. Negative: Refined Grains; Added Sugars; SFA; Sodium; DP Method(s): Index/Score Analysis; Comparisons: Continuous (per-10-pt) and categorical by tertiles with T1, HR: 1 REF | Follow-Up Duration: 13y, mean; Results for overall CRC:; HEI-2015 & CRC, HR: 1.13, 95% CI: 0.94, 1.36; Summary: NS/Positive: HEI-2015 & CRC | - Did not account for: Screening; - Diet assessment: FFQ (verified sub-set with RCT); - Outcome measurement: Incident cases identified by self-report, verified by physicians and/or medical records, NDI if LFU; Cx defined by ICD codes;; - BC cases identified: n=500; CRC cases identified: n=197); - Funding: NIH: NCI, NHLBI
Hoang, 2023^8^; United Kingdom; UK BIOBANK; Analytic N=374004; Participant characteristics:; - [underlined: Health]: BMI, OW: 43%, Ob: 24%; - [underlined: Race and/or Ethnicity]: 100% White British; - [underlined: SEP]: HH Income: 41% Low (31K); 23% Low-Mid (31K-<52K); 22% High (52K+); 14% missing; [underlined: Selection:] Excluded those with or who: missing genetic info, sex discordance, chromosome aneuploidy, were not White British, existing Cx | DP Age(s): 56.6y, mean (SD: 8); DP(s) examined: simplified WCRF/AICR Score (2018) - Diet Only [Choi, 2021 and Kaluza, 2020 modified Romaguera 2012]; DP Components:; - simplified WCRF/AICR-diet only, Positive: Non-starchy Vegetables, Fruit, Beans, and Whole grains; Dietary Fiber. Negative: Red and Processed Meat; Sugar-sweetened Drinks; Alcohol; Energy-Dense and “Fast” Foods (high in starch, fat, added sugar); DP Method(s): Index/Score Analysis; Comparisons: Categorical: Low WCRF (score 0-1) vs. high WCRF (2-3) HR: 1, REF | Follow-Up Duration: 12.4y, median; Results for overall CRC:; WCRF (Low (0-1) vs. high (2-3)) & overall CRC:; ♀+♂, HR: 1.12, 95% CI: 1.05, 1.19; ♂, HR: 1.18, 95% CI: 1.12, 1.31; ♀, HR: 1.02, 95% CI: 0.93, 1.12; IV-weighted WCRF & overall CRC:; ♀+♂,−2.88 to <1.09, HR: 1.14, 95% CI: 1.06, 1.23; ♀+♂, 1.09 to 13.02, HR: 1.27, 95% CI: 1.18, 1.37; p-trend<0.001; ♂, −2.88 to <1.09, HR: 1.26, 95% CI: 1.13, 1.40; ♂, 1.09 to 13.02, HR: 1.42, 95% CI: 1.28, 1.57; p-trend<0.001; ♀, −2.88 to <1.09, HR: 1.04, 95% CI: 0.93, 1.15; ♀, 1.09 to 13.02, HR: 1.11, 95% CI: 0.99, 1.24; p-trend=0.09; Summary: Inverse: WCRF & CRC | - Did not account for: SEP (not indicated in tables but indicated in methods text); Screening; - Diet assessment: 24-hr recalls, web-based; - Outcome measurement: NR, Cx defined by ICD codes; - n=4684 cases of CRC identified; - Funding: National Research Foundation of Korea (NRF)
Jin, 2023^9^; United States; Women’s Health Initiative, Dietary Modification (WHI-DM) Trial; Analytic N=112468; Participant characteristics:; - [underlined: Health]: BMI, mean: 26-30; 33-35% OW; 18-40% Ob across DP quintiles; - 100% postmenopausal; Smokers: 5-13% current; 12-14% use Aspirin/NSAIDs; - [underlined: Race and/or Ethnicity]: ~ 77-92% “White”, 4-16% “Black”, 2.5-8% “Hispanic/Latino”,1.3-5% “Asian/Pacific Islander”, 1-2% Other, < 1% “American Indian or Alaska Native”; - [underlined: SEP]: Education: ~28-51% ≥ 4y of college; ~46-62% high-school or less; [underlined: Selection:] Excluded those with or who: were in the DM arm; existing Cx; implausible/missing/extreme TEI/BMI; incomplete or missing FFQ at baseline; 4y lag or lower GI Dz (e.g., Chron’s); missing outcome | DP Age(s): 50 to 59y, ~40%;; 60 to 69y, ~43%;; 70 to 79y, ~16%; DP(s) examined: Empirical Dietary Indices for Hyperinsulinaemia (EDIH) [Tabung, 2016]; Empirical Dietary Inflammatory Pattern (EDIP) [Tabung, 2016]; Healthy Eating Index (HEI-2015) [Krebs-Smith 2018]; DP Components:; - EDIH: Positive: Red meat; Processed meat; Poultry; Tomatoes; French fries, Fish (non-dark); Low-fat dairy; Eggs; High-energy beverages (cola and other carbonated beverages with sugar, fruit drinks); Low-energy beverages; Margarine; Cream soups; Negative: Green leafy vegetables; Whole fruit; High-fat dairy products; Coffee; Wine; - EDIP, Positive (Anti-Inflammatory): Vegetables (dark yellow: carrots, or squash), Vegetables (leafy green: cabbage, spinach, lettuce); Fruit juice (apple, cantaloupe, orange, or other fruit juice); Pizza; Snacks (cracker, potato chips); Tea; Coffee. Negative (Pro-Inflammatory): Vegtables, other: mixed, green pepper, cooked mushroom, eggplant, zucchini, or cucumber); Processed meat (sausage); Red meat (beef, or lamb); Organ meat (beef, calf, or chicken liver), Fish, canned tuna; Refined grains (white bread, biscuit, white rice, pasta, or vermicelli); High- and low-energy beverages (cola with sugar, carbonated beverages with sugar, fruit punch drinks); Tomatoes; - HEI-2015: Positive: Total Vegetables; Greens and Beans; Total Fruit; Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; PUFA+MUFA/SFA. Negative: Refined Grains; Added Sugars; SFA; Sodium; DP Method(s): Index/Score Analysis; Comparisons: Continuous (per-SD) and categorical (quintiles, Q1, HR: 1 REF) | Follow-Up Duration: 17.8y, median; Results for overall CRC:; Overall CRC; EDIH; Q2, HR: 1.06(0.89,1.24); Q3, HR: 1.29(1.10,1.52); Q4, HR: 1.05(0.88,1.25); Q5, HR: 1.14(0.95,1.36); p-trend=0.21; per SD, HR: 1.05(0.99,1.11); p=0.1084; EDIP; Q2, HR: 1.13(0.95,1.34); Q3, HR: 1.17(0.98,1.41); Q4, HR: 1.17(0.96,1.42); Q5, HR: 1.18(0.96,1.46); p-trend=0.1295; per SD, HR: 1.07(0.99,1.15); p=0.0891; HEI-2015; Q2, HR: 0.97(0.83,1.13); Q3, HR: 0.92(0.78,1.08); Q4, HR: 0.84(0.72,1.00); Q5, HR: 0.88(0.75,1.04); p-trend=0.0468; per SD, HR: 0.94(0.89,0.99); p=0.0271; Summary: Positive: EDIH per SD & CRC, Colon Cx, Proximal Colon Cx; NS/Positive: Distal CRC or Q2, Q3, Q4; Positive: EDIP per SD & CRC, Colon Cx, Proximal Colon Cx; NS/Positive: Distal CRC or Q2, Q3, Q4; Inverse: HEI-2015 per SD & CRC, Colon Cx, Proximal Colon Cx; NS/Inverse: Distal CRC or Q2, Q3 | - Did not account for: Screening (BC only); - Diet assessment: FFQ (verified sub-set with RCT); - Outcome measurement: Incident cases identified by self-report, verified by physicians and/or medical records, NDI if LFU; Cx defined by ICD codes; Sub-types of BC defined by SEER; - Total Cx cases identified: n=18768; - Funding: NCI; ACS; NIH (NHLBI)
Kim, 2023^11^; United States; NHS; HPFS; Analytic N=211673; NHS-I; NHS-II; HPFS; Participant characteristics:; - [underlined: Health]: BMI, mean: ~24.7 to 26.2; - 4-8% DM; Smokers: 50-58% never; ~18-21% current HRT; ~ 31-41% reg. NSAID/Asprin use; - [underlined: Race and/or Ethnicity]: ~94-95% White; - [underlined: SEP]: NR; 100% health professionals; [underlined: Selection:] Excluded those with or who had: implausible/extreme TEI; did not respond post-baseline; Dx of Cx or IBD | DP Age(s): 65y, mean HPFS and NHS I; 49y, mean NHS-II (total range, 30 to 75y at baseline); DP(s) examined: Plant-Based Diet Index (PDI), healthful/unhealthful PDI (hPDI/uPDI) [Satija, 2016]; DP Components:; - PDI: Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Negative: Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; - hPDI: Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Negative: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; - uPDI: Negative: Whole grains; Fruits; Vegetables; Nuts; Legumes; Vegetable oils; Tea/coffee; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; Positive: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; DP Method(s): Index/Score Analysis; Comparisons: Continuous, per 1-SD (1 SD =10 units for PDI, 0.83 hPDI, 0.81 SD for uPDI) | Follow-Up Duration: NR, ~ 30y; Results for overall CRC:; PDI & CRC; ♀ + ♂, per-SD, HR: 0.98, 95% CI: 0.92, 1.05; ♀ NHS-I, per 10-pt, per-SD, HR: 1.03, 95% CI: 0.93, 1.14; ♀ NHS-II, per 10-pt, per-SD, HR: 0.99, 95% CI: 0.81, 1.20; ♂ HPFS, per 10-pt, per-SD, HR: 0.94, 95% CI: 0.85, 1.04; hPDI & CRC; ♀ + ♂, per-SD, HR: 0.94, 95% CI: 0.89, 1.00; ♀ NHS-I, per 10-pt & CRC, HR: 0.96, 95% CI: 0.88, 1.04; ♀ NHS-II, per 10-pt & CRC, HR: 0.92, 95% CI: 0.78, 1.08; ♂ HPFS, per 10-pt & CRC, HR: 0.93, 95% CI: 0.86, 1.02; uPDI & CRC; ♀ + ♂ CRC, per-SD, HR: 1.07, 95% CI: 1.01, 1.13; ♀ NHS-I, per 10-pt, HR: 1.07, 95% CI: 0.99, 1.16; ♀ NHS-II, per 10-pt, HR: 1.09, 95% CI: 0.94, 1.26; ♂ HPFS, per 10-pt, HR: 1.06, 95% CI: 0.97, 1.16; Summary: NS/Null: PDI & CRC, Colon, or Rectal Cx; NS/Null-Inverse: hPDI & CRC, Colon, or Rectal Cx; Positive: uPDI & CRC; NS/Positive: Colon; Rectal | - Did not account for: SEP, Screening; - Diet assessment: FFQ every 4y; - Outcome measurement: Incident cases determined by self-report, NDI; Tumor location and Dz stage from medical records & study physician; - n= 3794 CRC, n=2284 Colon Cx, n=759 Rectal Cx incident cases; - Funding: National Research Foundation of Korea (NRF); Ministry of Science and ICT (Korean govt.); NIH
Kim, 2022^10^; United States; Multi-Ethnic cohort; Analytic N=79952; Participant characteristics:; - [underlined: Health]: BMI, mean: 26.6 ♂ , 26.4 ♀; - Smokers: 69% ♂ , 44% ♀ Ever; - [underlined: Race and/or Ethnicity]: ~ 25-26% “White”, 13-19% “African - American”, 7% “Native Hawaiian”, 28-30% “Japanese American”; 21-24% “Latino”; - [underlined: SEP]: NR; [underlined: Selection:] Excluded those with or who had: invalid/incomplete data, pre-existing CRC, ethnicity other than 5 major groups specified, implausible TEI, missing covariates | DP Age(s): 60y mean; DP(s) examined: modified Plant-Based Diet Index (PDI), healthful/unhealthful PDI (hPDI/uPDI) [Kim 2022 modified Satija, 2016]; DP Components:; - mPDI: Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Fruit juices; Added sugars (SSB+Sweets); Refined grains; Potatoes; Negative: Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); - mhPDI: Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Negative: Fruit juices; Refined grains; Potatoes; Added sugars (SSB+Sweets); Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); - muPDI: Negative: Whole grains; Fruits; Vegetables; Nuts; Legumes; Vegetable oils; Tea/coffee; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; Positive: Fruit juices; Added sugars (SSB+Sweets); Refined grains; Potatoes; DP Method(s): Index/Score Analysis; Comparisons: Continuous (per-SD) and categorical (quintiles, Q1, HR: 1 REF) | Follow-Up Duration: 19.2y, mean; Results for overall CRC:; mPDI & CRC (95% CI); Q2, ♂ HR: 0.89 (0.79, 1.01); ♀ HR: 0.98 (0.86, 1.12); Q3, ♂ HR: 0.95 (0.84, 1.07); ♀ HR: 0.99 (0.86, 1.13); Q4, ♂ HR: 0.89 (0.78, 1.01); ♀ HR: 0.88 (0.77, 1.02); Q5, ♂ HR: 0.76 (0.67, 0.87); ♀ HR: 0.99 (0.86, 1.14); ♂ p-trend<0.001; ♀ p-trend=0.53; Associations by race/ethncity were strongest in Japanese-American and White men and NS for African American, Native Hawaiian and Latino men; In women, NS by race/ethnicity; mhPDI & CRC (95% CI); Q2, ♂ HR: 0.95 (0.84, 1.06); ♀ HR: 0.97 (0.85, 1.10); Q3, ♂ HR: 0.96 (0.85, 1.08); ♀ HR: 1.06 (0.93, 1.20); Q4, ♂ HR: 0.85 (0.75, 0.96); ♀ HR: 0.93 (0.81, 1.06); Q5, ♂ HR: 0.79 (0.69, 0.91); ♀ HR: 0.91 (0.80, 1.04); ♂ p-trend=0.0001; ♀ p-trend=0.14; muPDI & CRC (95% CI); Q2, ♂ HR: 0.93 (0.83, 1.05); ♀ HR: 0.96 (0.85, 1.09); Q3, ♂ HR: 0.97 (0.86, 1.10); ♀ HR: 0.96 (0.85, 1.09); Q4, ♂ HR: 0.96 (0.84, 1.09); ♀ HR: 0.97 (0.85, 1.11); Q5, ♂ HR: 1.08 (0.95, 1.22); ♀ HR: 1.01 (0.89, 1.15); ♂ p-trend=0.19; ♀ p-trend=0.85; Summary: Inverse: mPDI & overall CRC, left colon Cx, rectal Cx in ♂ (NS/null: mPDI & right colon Cx in ♂); NS/null in ♀ (all types); NS/Null: mhPDI & all types in ♂;; NS/Null: mhPDI & all types in ♀; NS/Null: muPDI & overall CRC, right colon Cx, left colon Cx in ♂ (NS/positive: muPDI & rectal Cx in ♂); NS/Null: in ♀ (all types) | - Did not account for: SEP, Screening; - Diet assessment: FFQ; - Outcome measurement: Incident cases identified via cancer registries or (deaths) via NDI; CX defined by ICD codes; - CRC cases identified: n=4976; - Funding: National Research Foundation of Korea (NRF); Ministry of Science and ICT (Korean govt.); NCI/NIH
Lee, 2023^12^; United States; NHS; HPFS; Analytic N=1189 (full-cohort analysis); 524 (case-control); Participant characteristics:; - [underlined: Health]: BMI, mean: ~25 (~34% OW; ~14% Ob); - Smokers: 43% never; ~29% current PM-HRT; - [underlined: Race and/or Ethnicity]: ~98% White; - [underlined: SEP]: NR; 100% health professionals; [underlined: Selection:] Excluded those with or who: implausible/extreme TEI; excessive missing FFQ data; Dx of Cx or IBD | DP Age(s): 60y, mean (total range, 30 to 75y at baseline); DP(s) examined: Empirical Dietary Indices for Hyperinsulinaemia (EDIH) [Tabung, 2016]; Empirical Dietary Inflammatory Pattern (EDIP) [Tabung, 2016] Healthy Eating Index (HEI-2015) [Krebs-Smith 2018]; DP Components:; - EDIH, Positive: Red meat; Processed meat; Poultry; Tomatoes; French fries, Fish (non-dark); Low-fat dairy; Eggs; High-energy beverages (cola and other carbonated beverages with sugar, fruit drinks); Low-energy beverages; Margarine; Cream soups; Negative: Green leafy vegetables; Whole fruit; High-fat dairy products; Coffee; Wine; - EDIP, (revserse coded), Positive (Anti-Inflammatory): Vegetables (dark yellow: carrots, or squash), Vegetables (leafy green: cabbage, spinach, lettuce); Fruit juice (apple, cantaloupe, orange, or other fruit juice); Pizza; Snacks (cracker, potato chips); Tea; Coffee; Beer; Wine. Negative (Pro-Inflammatory): Vegetables, other: mixed, green pepper, cooked mushroom, eggplant, zucchini, or cucumber); Processed meat (sausage); Red meat (beef, or lamb); Organ meat (beef, calf, or chicken liver), Fish, canned tuna; Refined grains (white bread, biscuit, white rice, pasta, or vermicelli); High- and low-energy beverages (cola with sugar, carbonated beverages with sugar, fruit punch drinks); Tomatoes; - HEI-2015: Positive: Total Vegetables; Greens and Beans; Total Fruit; Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; PUFA+MUFA/SFA. Negative: Refined Grains; Added Sugars; SFA; Sodium; DP Method(s): Index/Score Analysis; Comparisons: Continuous per-SD for EDIH and EDIP (i.e., higher scores=more inflammatory/insulinemic) | Follow-Up Duration: NR, ~ 30y; Results for overall CRC:; (95% CI); EDIP, case-control, per SD & CRC (95% CI), ♂ OR: 1.47 (1.03, 2.09), p=0.03; ♀ OR: 1.12 (0.94, 1.34), p=0.21; EDIP, full cohort, per SD & CRC: ♂ OR: 1.17 (1.09, 1.26), p<0.001; ♀ OR: 1.08 (1.02, 1.16), p=0.02; EDIH, case-control, per SD & CRC (95% CI), ♂ OR: 1.20 (0.89, 1.63), p=0.24; ♀ OR: 1.27 (1.07, 1.50), p=0.006; EDIH, full cohort, per SD & CRC: ♂ OR: 1.13 (1.06, 1.22), p<0.001; ♀ OR: 1.08 (1.01, 1.15), p=0.03; Summary: Positive: EDIP per SD in ♂ or ♀ in the full cohort or case-control ♂ & CRC; NS/Positive: case-control ♀; Positive: EDIH per SD in ♂ or ♀ in the full cohort or case-control ♀ & CRC; NS/Positive: case-control ♂ | - Did not account for: SEP; - Diet assessment: FFQ (verified sub-set with RCT); - Outcome measurement: Incident cases determined by self-report, NDI and included only confirmed cases from medical record/study physician review; - n= 3794 CRC, n=2284 Colon Cx, n=759 Rectal Cx incident cases; - Funding: NIH; Yonsei Signature Research Cluster Project; Yonsei University Research Fund
Liu, 2023^13^; United Kingdom; UK BIOBANK; Analytic N=186675; Participant characteristics:; - [underlined: Health]: BMI, OW: 42%; Ob 21%; - Smokers: 53-60% never; - [underlined: Race and/or Ethnicity]: ~ 95% “White”, 1.1-1.6% “Black”, 1.3-1.6% “Asian”, 0.6% “Mixed”, 0.3% “Chinese”, ~0.8% Other, 0.4% Unknown; - [underlined: SEP]: Townsend: ~−2.1 to −2.4;; - Education: 43% university/college; [underlined: Selection:] Excluded those with or who: <1 diet assessment, did not have genetic data; implausible/extreme TEI; Dx of Cx | DP Age(s): ~58y, mean across PDI quintiles (range 37 to 73y at baseline); DP(s) examined: modified Plant-Based Diet Index (PDI), healthful/unhealthful PDI (hPDI/uPDI) [Kim modified Satija, 2016 (UK BIOBANK did not include data on vegetable oils)]; DP Components:; - mPDI: Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Tea/coffee; Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Negative: Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; - mhPDI: Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Tea/coffee; Negative: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; - muPDI: Negative: Whole grains; Fruits; Vegetables; Nuts; Legumes; Tea/coffee; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; Positive: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; DP Method(s): Index/Score Analysis; Comparisons: Continuous, per 10unit increases and Categorical, by quartiles (Q1, HR: 1 REF) | Follow-Up Duration: 9.5y, mean; Results for overall CRC:; PDI & CRC (95% CI); Q2, HR: 0.94 (0.83, 1.06); Q3, HR: 0.92 (0.81, 1.05); Q4, HR: 0.87 (0.77, 0.99); p-trend=0.0318; per10, HR: 0.88 (0.81, 0.96); hPDI & CRC; Q2, HR: 0.96 (0.85, 1.08); Q3, HR: 0.91 (0.81, 1.03); Q4, HR: 0.85 (0.75, 0.97); p-trend=0.0122; per10, HR: 0.91 (0.84, 0.99); uPDI & CRC; Q2, HR: 1.18 (1.04, 1.33); Q3, HR: 1.08 (0.95, 1.22); Q4, HR: 1.14 (1.01, 1.30); p-trend=0.1542; per10, HR: 1.05 (0.97-1.13); Summary: Inverse: mPDI (per10; Q4)& CRC and Rectal Cx; NS/Inverse: Proximal or Distal Colon Cx; Inverse: mhPDI (per10; Q4)& CRC and Rectal Cx; NS/Inverse: Proximal or Distal Colon Cx; Positive: muPDI (Q2, Q4) & CRC and Distal Colon Cx; NS/Positive: Proximal Colon or Rectal Cx | - Did not account for: Screening; - Diet assessment: 24-hr recalls, web-based; - Outcome measurement: Incident cases identified via medical records, cancer or death registries; CX defined by ICD codes; - CRC cases identified: n=2163; - Funding: National Key R&D Program of China; National Natural Science Foundation of China, Tianjin Key Medical Discipline (Specialty) Construction Project, the Young Elite Scientists Sponsorship Program by China Association for Science and Technology; Guang dong Basic and Applied Basic Research Foundation
Maimaitiyiming, 2023^14^; United Kingdom; UK BIOBANK; Analytic N=114289; Participant characteristics:; - [underlined: Health]: BMI, mean: 25-28.5; - 17-27% HTN, 2-7% DM; 2-6% CVD; Smokers: 49-62% never; ~33-36% current HRT; - [underlined: Race and/or Ethnicity]: ~100% White; - [underlined: SEP]: Townsend: ~−1.48 to −1.77;; - Education: 84-94% higher/degree; [underlined: Selection:] Excluded those with or who: <1 diet assessment; Dx of Cx; implausible/extreme TEI; withdrew | DP Age(s): ~56y, mean across DP quartiles (40-69 y at baseline); DP(s) examined: “Obesity-related” DP; DP Components:; - DP characterized by: Higher intake of beer and cider, processed meat, high-sugar beverages, red meat, and artifcial sweetener (Other positive loadings, 0.40 to 0.10: Crisps, chips, savory snacks; instant coffee; spirits/liquors; ice cream; frozen vegetable; egg and egg dishes; added sugars; breaded meat/fish; buns, cakes etc.; white bread; poultry; other breakfast cereals; PUFA margarine; boiled/baked potato; liver; legumes); Lower intake of fresh vegetables, olive oil, tea, and high fber breakfast cereals (Other negative loadings, −0.20 to 0.0: water; other milk; nuts and seeds; fruits; cereals; meat alternatives; oily fish; whole grain cereals; low-fat butter; other coffee; other fish; low-fat cheese; wine); DP Method(s): RRR; Comparisons: Categorical (quartiles, Q1, HR: 1 REF) and linear trend | Follow-Up Duration: 9.4y, median; Results for Overall CRC:; DP & CRC (95% CI); linear, HR: 1.08(1.04,1.12); Q2, HR: 1.04(0.94,1.15); Q3, HR: 1.12(1.02,1.24); Q4, HR: 1.2(1.08,1.33); p=0.001; Complete-case, HR: 1.10 (1.06, 1.15); p<0.001; Similar CRC risk by age (</> 65y); Summary: Positive: “Obesityrelated” DP & CRC | - Did not account for: Screening; - Diet assessment: 24-hr recalls, web-based; - Outcome measurement: Methods NR; Cx defined by ICD; - CRCx, n=1218; Premenopausal BCx, n=809; postmenopausal BCx, n=1190; - Funding: None reported for study
Moazzen, 2022^15^; The Netherlands; Lifelines; Analytic N=72695; Participant characteristics:; - [underlined: Health]: BMI, mean: 26.5; - Smokers: 7.4 pk/y; - [underlined: Race and/or Ethnicity]: NR (100% Dutch nationality); - [underlined: SEP]: Education: 37% low, 36% medium, 26% high; [underlined: Selection:] Excluded those with or who: missing data/unreliable diet; Hx or Dx of Cx | DP Age(s): 51.2y, mean (SD: 8.71); DP(s) examined: Dutch Dietary Guidelines - 2015 [Kromhout, 2016]; Lifelines Diet score (LLDS) [Vinke, 2018]; American Cancer Society Index, ACS-diet only [Kabat, 2015]; WCRF/AICR Score - Diet Only [Romaguera 2012]; DP Components:; - DDG, Positive: Vegetables; Legumes; Fruit; Nuts, unsalted; Whole Grains; Fish; Liquid cooking fats, Vegetable Oils, Soft Margarine; Tea. Negative: Red and Processed Meat; Sugar-Sweetened Beverages; Alcohol; - LLS, Positive: Vegetables; Fruit; Legumes and Nuts; Whole Grains; Fish; Oils and Soft Margarines; Unsweetened Dairy; Tea; Coffee (Filtered); Negative: Red and processed meats; Sugar-sweetened beverages; Butter and Hard Margarines; - ACS-diet, Positive: Vegetables; Fruit; Whole Grains; Negative: Red and Processed Meat; Alcohol; - WCRF/AICR-diet only, Positive: Vegetables and Fruit; Dietary Fiber. Negative: Red and Processed Meat; Sugary Drinks; Alcohol; Sodium; Energy-Dense Foods; DP Method(s): Index/Score Analysis; Comparisons: Categorical for each DP by quintiles (Q1, HR: 1 REF) and linear trend | Follow-Up Duration: 8y, mean (2y IQR); Results for Overall CRC:; DDG & CRC (95% CI); Q2, HR: 0.84 (0.61, 1.17); Q3, HR: 0.92 (0.68, 1.25); Q4, HR: 0.90 (0.66, 1.23); Q5, HR: 0.79 (0.57, 1.09); p-trend=0.61; LLS & CRC; Q2, HR: 0.87 (0.63, 1.20); Q3, HR: 0.83 (0.60, 1.16); Q4, HR: 0.72 (0.52, 1.01); Q5, HR: 0.94 (0.68, 1.30); p-trend=0.29; ACS-diet & CRC; Q2, HR: 0.91 (0.65, 1.26); Q3, HR: 0.75 (0.57, 0.99); Q4, HR: 0.65 (0.46, 0.92); Q5, HR: 0.68 (0.49, 0.93); p-trend=0.6; WCRF/AICR-diet & CRC; Q2, HR: 0.98 (0.71, 1.35); Q3, HR: 0.96 (0.70, 1.31); Q4, HR: 1.01 (0.74, 1.38); Q5, HR: 0.90 (0.65, 1.26); p-trend=0.96; Summary: NS/Inverse: DDG & CRC; NS/Inverse: LLS & CRC; Inverse/NS: ACS-diet (Q2, Q3, Q4) & CRC; NS/Inverse: WCRF/AICR-diet & CRC | - Did not account for: Sex, Race/Ethnicity (Dutch), Screening; - Diet assessment: FFQ; - Outcome measurement: Incident cases identified via registry; - CRC cases identified: n=434; - Funding: NR
Neuhouser, 2022^16^; United States; Women Health Initiative (WHI); Analytic N=100374; Participant characteristics:; - [underlined: Health]: BMI, mean: 27.6; - Smokers: 51% never; 40% current HRT; - [underlined: Race and/or Ethnicity]: 84.5% White, non-Hispanic; 7.7% Black, non-Hispanic; 3.3% Hispanic/Latina; 2.8% Asian/Pacific Islander; - SEP: Education: 42.4% ≥ college degree; [underlined: Selection:] Excluded those with Hx of CVD | DP Age(s): 63.6y, mean (50 to 79 y); DP(s) examined: HEI-2010; DP Components:; - HEI-2010, Positive: Total Vegetables; Greens and Beans; Total Fruit; Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; Fatty Acids. Negative: Refined Grains; Added Sugars in “Empty Calories”; Solid Fats in “Empty Calories”; Sodium; DP Method(s): Index/Score; Comparisons: Continuous, per 20% increment in HEI-2010 scores [Uncalibrated (Uncal), Calibrated (Cal) for biomarkers] | Follow-Up Duration: 22-26y ~; Results for Overall CRC:; - HEI-2010 (Uncal per 20%) & CRC, HR: 0.94, 95% CI: 0.89, 1.00; - HEI-2010 (Cal per 20%) & CRC, HR: 0.90, 95% CI: 0.71, 1.14; Summary: NS/Inverse: HEI-2010 & CRC | - Did not account for: Screening; - Diet assessment: FFQ (verified sub-set with RCT); - Outcome measurement: Incident cases identified via self-report then confirmed via medical records/pathology with physician review;; - cases identified: n=2364 (BCx); n=2315 (CRCx); - Funding: NIH/NHLBI
Nguyen, 2020^17^; China; Shanghai Women’s Health Study (SWHS); Shanghai Men’s Health Study (SMHS); Analytic N=132606; Participant characteristics:; - [underlined: Health]: BMI: OW: 24%; Ob: ~19%; - 45% with 1+ HTN, DM, CVD and/or OW/Ob; Smokers: 72% never; - [underlined: Race and/or Ethnicity]: NR (100% Chinese); - [underlined: SEP]: Income: 16% low, 42% lowmid, 30% upper-mid, 13% high; Education: 25% elementary or less, 31% middle, 27% high school, 17% college+; [underlined: Selection:] Excluded those with or who: missing/incomplete FFQ; implausible TEI; Dx of Cx; or <2y of F/U; Excluded data from first 2y F/U | DP Age(s): 60.5y, mean total (those w CRC); 51.5, mean total (those w/out CRC) (40-74 y at baseline); DP(s) examined: CHFP & CRC; mAHEI-2010 & CRC; mDASH & CRC; DP Components:; - CHFP, Positive: Vegetables; Fruits; Beans; Grains; Fish and shrimp; Dairy. Negative: Meat and poultry; Eggs; Fats and oils; Salt; - mAHEI-2010: Positive: Vegetables (not potatoes, French fries); Fruit; Legumes and Nuts; Long-Chain Fats (EPA + DHA); PUFA. Negative: Red and Processed Meat; Sodium; Moderate: Alcohol (Removed whole grains, SSBs, trans FA); - mDASH: Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Dairy. Negative: Red and Processed Meat; Sodium (Removed whole grains, SSBs; all Dairy v. low-fat); DP Method(s): Index/Score; Comparisons: Continuous (per-SD) and categorical (quartiles, Q1, HR: 1 REF) | Follow-Up Duration: 8.1y, mean for ♂; 13.4y, mean for ♀; Results for overall CRC:; CHFP & CRC; Q2, HR: 0.88 (0.77, 1.00); Q3, HR: 0.86 (0.75, 0.98); Q4, HR: 0.84 (0.73, 0.96); p-trend=0.01; per-SD, HR: 0.94 (0.90, 0.99), p=0.02; mAHEI-2010 & CRC; Q2, HR: 0.92 (0.80, 1.05); Q3, HR: 0.94 (0.83, 1.08); Q4, HR: 0.91 (0.79, 1.05); p-trend=0.27; perSD, HR: 0.96 (0.92, 1.01); p=0.13; mDASH & CRC; Q2, HR: 0.92(0.80,1.05); Q3, HR: 0.98(0.86,1.12); Q4, HR: 0.90(0.78,1.03); p-trend=0.23; perSD, HR: 0.96(0.91,1.01); p=0.15; Summary: Inverse: CHFP & CRC and Rectal Cx; NS: Colon Cx; NS/Inverse: mAHEI-2010 & CRC; Colon Cx; Rectal Cx; NS/Inverse: mDASH & CRC; Colon Cx; Rectal Cx | - Did not account for: Race/Ethnicity (100% Chinese), Screening; - Diet assessment: FFQ (verified sub-set with 24h recalls in parent studies); - Outcome measurement: Incident cases identified via registry and verified; Cx defined by ICD; - CRC cases identified: n=1670; - Funding: NIH
Petermann-Rocha, 2021^18^; United Kingdom; UK BIOBANK; Analytic N=422702; Participant characteristics:; - [underlined: Health]: BMI, mean: 26.7-28.1; 42% OW 24% Ob:; - 5% DM; 29% CVD; Smokers: 42-61% never; - [underlined: Race and/or Ethnicity]: ~95% White, 1.8% “South Asian”, 1.5% “Black”, 1.4% “Mixed”, 0.3% “Chinese”; - [underlined: SEP]: ~29-36% Lower; ~32-34% Mid; ~29-40% High (based on deprivation index); [underlined: Selection:] Excluded those with or who: missing data (diet, Cx, covariates); Dx of Cx; implausible/extreme TEI; withdrew | DP Age(s): ~56y, mean across DP quartiles (37-73 y at baseline); DP(s) examined: Dietary risk score (DRS) [Petermann-Rocha, 2021]; DP Components:; - Positive: Red Meat; Processed Meat; Whole-milk; Spread (Butter, Other/ margarine, and/or Flora proactive/benecol); Salt added to food; Negative: Vegetables and Fruit; Cereals; Total Fish; Water.; DP Method(s): Index/score; Comparisons: Continuous, DRS (higher scores ~ higher risk and lower recommendations met) | Follow-Up Duration: 9y, median; Results for Overall CRC:; DRS & CRC, HR: 1.05, 95% CI: 1.03, 1.07; Summary: Positive: DRS & CRC | - Did not account for: Screening, Postmenopausal hormone therapy (BC only); - Diet assessment: 24-hr recalls, web-based; - Outcome measurement: Incident cases identified via registry, national health services, information center, hospital records; CX defined by ICD codes; - Total Cx, n= 42,767 (includes GI Cx, CRCx, BCx, Prostate Cx); - Funding: come Trust medical charity, Medical Research Council,; - Department of Health, Scottish Government, and the; - Northwest Regional Development Agency. It has also had; - Wellcome Trust medical charity; Medical Research Council, Dept. of Health Scottish Government; Welsh Assembly Government; British Heart Foundation.
Ren, 2023^19^; United States; Prostate, Lung, Colorectal, and Ovarian (PLCO) Cancer Screening Trial; Analytic N=98415; Participant characteristics:; - [underlined: Health]: BMI NR; - 32% HTN; Smokers: 48% never; - 12.6 % with Family Hx CRCx; - [underlined: Race and/or Ethnicity]: 93% White; - [underlined: SEP]: NR; [underlined: Selection:] Excluded those with or who: missing baseline questionnaire; invalid FFQ; missing 8+ FFQ items; Hx of Cx; withdrew; implausible/extreme TEI | DP Age(s): 65.5y (55 to 74y at baseline); DP(s) examined: EAT-Lancet Reference Diet [Vallejo, 2022; EAT-Lancet Commission, 2019]; DP Components:; - EAT-Lancet: Positive: Whole grains & all grains, ≤ 464 g/d and whole grain fiber; Vegetables, ≥ 200 - ≤ 600 g/d; Fruits, ≥ 100 - ≤ 300 g/d; All nuts, ≥ 25 g/d. Negative: Dairy foods, ≤ 500 g/d; Beef and lamb, ≤ 14 g/d; Pork, ≤ 14 g/d; Chicken and other poultry, ≤ 58 g/d; Eggs, ≤ 25 g/d; Fish, ≤ 100 g/d; Dry beans, lentils & peas, ≤ 100 g/d; Soy foods, ≤ 50 g/d; Palm oil, ≤ 6.8 g/d; Lard or tallow, ≤ 5 g/d; Butter, 0 g/d; All sweeteners, ≤ 31 g/d. Neutral: Tubers or starchy vegetables, ≤ 100 g/d; Unsaturated oils, ≥ 20 - ≤ 80 g/d; DP Method(s): Index/score; Comparisons: Categorical and linear trend (quartiles, Q1, HR: 1 REF) | Follow-Up Duration: 8.8y, mean; Results for Overall CRC:; EAT-Lancet & CRC; Q2, HR: 0.81 (0.69, 0.95); Q3, HR: 0.84 (0.70, 0.99); Q4, HR: 0.81 (0.673, 0.98); p-trend=0.034; Summary: Inverse: EAT-Lancet & CRC; NS/Inverse: Proximal or Distal Colon Cx or Rectal Cx | - Did not account for: SEP, Screening; - Diet assessment: FFQ; - Outcome measurement: Incident cases identified via self-report then confirmed via medical records/pathology; - Cases identified: n=1054; - Funding: General Project of Chongqing Natural Science Foundation, Chongqing Science and Technology Commission, China; Kuanren Talents Project of the Second Affiliated Hospital of Chongqing Medical University in China
Schulpen, 2020^20^; Netherland; The Netherlands Cohort Study; Analytic N=8050 in total; 4084 subcohort members; 3966 case; Participant characteristics:; - [underlined: Health]: BMI, mean, kg/m2: ♂ 24.9, ♀ 25 (cases: ♂ 25.2; ♀ 25);; - Smokers: former ♂ 52%, ♀ 23% (cases: ♂ 58%; 23%);; - Family Hx CRC: ♂ 5%, ♀ 6% (cases, 9% , 10%; - [underlined: Race and/or Ethnicity]: NR (Dutch); - [underlined: SEP]: Higher vocational education or university, 19.3-21.0% in men; 9.5% in women; [underlined: Selection:] Excluded those who had a history of cancer at baseline (except skin cancer), did not have complete and consistent dietary data, did not have data available on alcohol consumption and MD adherence | DP Age(s): 61y, mean (55-69y); DP(s) examined: Alternate Med Diet Score (aMED) [Fung 2005]; Alternate Med Diet Score (aMEDr)[Fung 2005] with alcohol removed; WCRF/AICR [Romaguera 2012], [van den Brandt PA, 2017]; DP Components:; - aMED, Positive: Vegetables (not potatoes); Legumes; Fruit; Nuts; Whole Grains; Fish; MUFA/SFA. Negative: Red and Processed Meat. Neutral: Alcohol; - aMEDr, Positive: Vegetables (not potatoes); Legumes; Fruit; Nuts; Whole Grains; Fish; MUFA/SFA. Negative: Red and Processed Meat. [aMEDr removed alcohol]; - WCRF/AICR-diet only, Positive: Vegetables and Fruit; Dietary Fiber. Negative: Red and Processed Meat; Sugary Drinks; Alcohol; Sodium; Energy-Dense Foods; DP Method(s): Index/Score Analysis; Comparisons: Categorical: low (0-3)(ref, HR 1), middle (4-5), and high (6-8(9)); Continuous: per two-point per SD-increment of WCRF/AICR | Follow-Up Duration: 20.3 y; Results for Overall CRC:; In Men; aMEDr & CRC; 4-5, HR: 1.07, 95% CI: 0.92, 1.24; 6-8, HR: 1.04, 95% CI: 0.85, 1.28; P for trend=0.654; Per 2 pts, HR 1.04, 95% CI: 0.95, 1.13; aMED & CRC; 4-5, HR 1.04, 95% CI: 0.88, 1.21; 6-8, HR 1.07, 95% CI: 0.89, 1.28; P for trend=0.5; Per 2 pts, HR 1.03, 95% CI: 0.95, 1.12; WCRF/AICR (excluding alcohol) & CRC, Per SD: HR 0.99, 95% CI: 0.93, 1.07; aMEDr & CRC, per SD: HR 1.03, 95% CI: 0.96, 1.10; WCRF/AICR with alcohol & CRC, per SD: HR 0.95, 95% CI:0.88, 1.02; aMED & CRC, per SD: HR 1.02, 95% CI: 0.96, 1.10; In women; aMEDr & CRC; 4-5, HR 0.86, 95% CI: 0.73, 1.00; 6-8, HR 1.01, 95% CI: 0.82, 1.23; P for trend=0.941; Per 2 pts, HR 0.97, 95% CI: 0.88, 1.07; aMED & CRC; 4-5, HR 0.86, 95% CI: 0.73, 1.01; 6-9, HR 0.97, 95% CI: 0.80, 1.18; P for trend=0.960; Per 2 pts, HR 0.97, 95% CI: 0.89, 1.06; WCRF/AICR (excluding alcohol) & CRC, Per SD: HR 0.99, 95% CI: 0.92, 1.07; aMEDr & CRC, per SD: HR 0.98, 95% CI: 0.91, 1.05; WCRF/AICR with alcohol & CRC, per SD: HR 1.00, 95% CI:0.92, 1.07 aMED & CRC, per SD: HR 0.97, 95% CI: 0.90, 1.05; Summary: NS/Null: aMED & CRC, colon, distal, proximal and rectal colon in both men and women; NS/Null: aMEDr & CRC, colon, distal, proximal and rectal colon in both men and women; NS/Null: WCRF/AICR diet score (including and excluding alcohol) & CRC, colon, distal, proximal and rectal colon in both men and women | - Did not account for: Race/Ethnicity, Screening; - Diet assessment: FFQ; - Outcome measurement: Incident cases identified via annual record linkage with the Netherlands Cancer Registry and the nationwide Dutch Pathology Registry; microscopically confirmed; - Funding: Wereld Kanker Onderzoek Fonds Nederland, World Cancer Research Fund International grant program
Shang, 2023^21^; United Kingdom; UK BIOBANK; Analytic N=121513; Participant characteristics:; - [underlined: Health]: BMI,; - Smokers, current: 4-11%; - [underlined: Race and/or Ethnicity]: 94-98% White; - [underlined: SEP]: Education, high (≥ 13y): 39-54%; - HH Income (pounds), 18K-30,999: 28-33%; 31K-51,999: 26-27%; 52K-100K: 20-25%; >100K: 5-9%; [underlined: Selection:] Excluded individuals with no data on diet, or with only one dietary assessments, or with total energy intake in either the highest or lowest percentile, or with prevalent cancer of interest for analysis at baseline | DP Age(s): 59y, mean (range: 30 to 75y); DP(s) examined: Alternate Med Diet Score (aMED) [Fung 2005]; “AEDII”=Empirical dietary inflammatory pattern (EDIP) [Tabung, 2016]; Alternative HEI (AHEI)-2010 [Chiuve 2012]; Healthful PDI (hPDI) [Satija, 2016]; DP Components:; - aMED: Positive: Vegetables (not potatoes); Legumes; Fruit; Nuts; Whole Grains; Fish; MUFA/SFA. Negative: Red and Processed Meat. Neutral: Alcohol; - EDIP (“AEDII”): Anti-inflammatory group: tea, coffee, dark yellow vegetables (carrots, or squash), leafy green vegetables (cabbage, spinach, or lettuce), snacks (cracker, or potato chips), fruit juice (apple juice, cantaloupe juice, orange juice, or other fruit juice), pizza Pro-inflammatory group: processed meat (sausage), red meat (beef, or lamb), organ meat (beef, calf, or chicken liver), other fish (canned tuna, or fish), other vegetables (mixed vegetables, green pepper, cooked mushroom, eggplant, zucchini, or cucumber), refined grains (white bread, biscuit, white rice, pasta, or vermicelli), high-energy and low energy beverages (cola with sugar, carbonated beverages with sugar, fruit punch drinks), and tomatoes; - AHEI-2010: Positive: Vegetables (not potatoes, French fries); Fruit; Legumes and Nuts; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA. Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Trans FA; Sodium. Neutral: Alcohol; - hPDI: Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Negative: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; DP Method(s): Index/Score Analysis; Comparisons: Categorical: quintiles (Q1 ref, HR 1); Continuous: each quintile increment | Follow-Up Duration: ~8.5 y; Results for Overall CRC:; aMED & Colon cancer; Q2, HR 0.94, 95% CI: 0.75, 1.18; Q3, HR 0.80, 95% CI: 0.64, 1.01; Q4, HR 0.94, 95% CI: 0.75, 1.18; Q5, HR 0.81, 95% CI: 0.64, 1.01; P for trend=0.19; Per quintile increment, HR 0.96, 95% CI: 0.91, 1.01; EDIP (AEDII) & Colon cancer; Q2, HR 0.82, 95% CI: 0.65, 1.04; Q3, HR 0.86, 95% CI: 0.69, 1.08; Q4, HR 0.87, 95% CI: 0.70, 1.09; Q5, HR 0.97, 95% CI: 0.78, 1.21; P for trend=0.36; Per quintile increment, HR 1.00, 95% CI: 0.95, 1.05; AHEI-2010 & Colon cancer; Q2, HR 1.06, 95% CI: 0.85, 1.32; Q3, HR 1.13, 95% CI: 0.91, 1.41; Q4, HR 1.01, 95% CI: 0.81, 1.26; Q5, HR 0.83, 95% CI: 0.65, 1.05; P for trend=0.0993; Per quintile increment, HR 0.96, 95% CI: 0.91, 1.01; hPDI & Colon cancer; Q2, HR 0.85, 95% CI: 0.64, 1.14; Q3, HR 0.94, 95% CI: 0.77, 1.14; Q4, HR 0.91, 95% CI: 0.74, 1.12; Q5, HR 0.72, 95% CI: 0.57, 0.91; P for trend=0.0763; Per quintile increment, HR 0.94, 95% CI: 0.89, 0.99; Summary: NS/Inverse: aMED & Colon cancer; NS/Null: EDIP(AEDII) & Colon cancer; NS/Inverse: AHEI-2010 & Colon cancer; Inverse: hPDI (Q5 vs. Q1; per quintile) & Colon Cancer | - Did not account for: Screening; PM HRT for BC; - Diet assessment: FFQ; - Outcome measurement: Incident cases identified using inpatient hospital records and mortality registers, using ICD9 or ICD10; - Funding: GDPH Supporting Fund for Talent Program; National Natural Science Foundation of China; Research Foundation ○ Medical Science and Technology of Guangdong Province; National Natural Science Foundation of China; Outstanding Young Talent Trainee Program of Guangdong Provincial People’s Hospital; Guangdong Provincial People’s Hospital Scientific Research Funds for Leading Medical Talents and Distinguished Young Scholars in Guangdong Province; Talent Introduction Fund of Guangdong Provincial People’s Hospital; High-level Talent Flexible Introduction Fund of Guangdong Provincial People’s Hospital; University of Melbourne at Research Accelerator Program and the CERA Foundation; Operational Infrastructure Support from the Victorian State Government.
Thompson, 2023^22^; United Kingdom; UK BIOBANK; Analytic N=126394; Participant characteristics:; - [underlined: Health]: BMI, OW: 42%; Ob 21%; - Smokers: 53-60% never; - [underlined: Race and/or Ethnicity]: 91% “White”, 0.4% “Black”, 4.6% “Asian”, 2.8% “Multiple”, <1% Unknown/Other; - [underlined: SEP]: Townsend: ~−2.1 to −2.4;; - Education: 43% university/college; [underlined: Selection:] Excluded those with or who: < 2 diet assessment; missing data on diet/covariates; implausible/extreme TEI; Dx of Cx | DP Age(s): 56.1y, mean across PDI quintiles (range: 37-73y at baseline); DP(s) examined: Plant-Based Diet Index - healthful (hPDI)/unhealthful PDI (uPDI), modified [modified Satija, 2016; UK BIOBANK did not include data on vegetable oils)]; DP Components:; - mhPDI: Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Tea/coffee; Negative: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; - muPDI: Negative: Whole grains; Fruits; Vegetables; Nuts; Legumes; Tea/coffee; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; Positive: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; DP Method(s): Index/Score Analysis; Comparisons: Continuous, per 10-unit increases and Categorical, by quartiles (Q1, HR: 1 REF) | Follow-Up Duration: 10.6 to 12.2y, mean; Results for Overall CRC:; hPDI & CRC (95% CI); Q2, HR: 1.01 (0.85, 1.21); Q3, HR: 0.92 (0.77, 1.11); Q4, HR: 0.87 (0.72, 1.05); p-corrected=0.22; uPDI & CRC (95% CI); Q2, HR: 1.20 (1.01, 1.42); Q3, HR: 1.19 (1.00, 1.42); Q4, HR: 1.05 (0.86, 1.27); p-corrected=0.22; Summary: NS/Inverse: hPDI & CRC; NS/PositivE: uPDI & CRC | - Did not account for: Screening; - Diet assessment: 24-hr recalls, web-based; - Outcome measurement: Incident cases identified via registry (information center) and/or medical records; CX defined by ICD codes; - Cases identified: n=1083 postmenopasual BC; n=959 CRC; - Funding: Wellcome Trust medical charity, Medical Research Council, Department of Health, Scottish Government, and the Northwest Regional Development Agency; Medical Research Council, Dept. of Health Scottish Government; Welsh Assembly Government; British Heart Foundation, Diabetes United Kingdom, the Northwest Regional Development Agency.
Wang, 2023^25^; United States; NHS; HPFS; Analytic N=218181; Participant characteristics:; - [underlined: Health]: BMI, mean: 24.2-26.2 (Q1 vs. Q5 across DPs); - Smoking ~7-12 pack-years; - [underlined: Race and/or Ethnicity]: Predominantly White; - [underlined: SEP]: NR (all health professionals); [underlined: Selection:] Excluded those with or who had: implausible/extreme TEI; missing data; Dx of Cx or IBD | DP Age(s): 65y, mean HPFS-NHS I; 49y, mean NHS-II (range: 30 to 75y at baseline); DP(s) examined: “Prudent” DP via PCA; “Western” DP via PCA; WCRF/AICR Score - Diet Only [Romaguera 2012]; Colorectal cancer dietary score (CRC) [no citation]; Alternative HEI (AHEI)-2010 [Chiuve 2012]; Alternate Mediterranean diet score (aMED) [Fung, 2005]; DASH diet score [Fu; DP Components:; - “Prudent” and “Western” DP not clearly reported, but included the following components: Fruit, cruciferous vegetables, yellow vegetables, leafy vegetables, other vegetables, tomatoes, whole grains, legumes, refined grains, snacks, French fries, pizza, desserts, red meat, processed meat, low-energy beverages, sugar-sweetened beverages, fruit juice, wine, beer, liquor, water, tea, coffee, low-fat dairy, high-fat dairy, creamy soups, condiments, salad dressing, olive oil, butter, margarine, mayonnaise, garlic, potatoes, nuts, eggs, poultry meat, fish, and organ meat.; - WCRF/AICR-diet only, Positive: Vegetables and Fruit; Dietary Fiber. Negative: Red and Processed Meat; Sugary Drinks; Alcohol; Sodium; Energy-Dense Foods (“UPF”); - CRC, Positive: Whole grains; Dairy products; Fiber; Calcium supplements. Negative: Red meats; Processed meats; Alcoholic drinks; - AHEI-2010: Positive: Vegetables (not potatoes, French fries); Fruit; Legumes and Nuts; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA. Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Trans FA; Sodium; Moderate: Alcohol; - aMED: Positive: Vegetables (not potatoes; Legumes; Fruit (not juices); Nuts; Whole Grains; Fish & shell fish; MUFA/SFA. Negative: Red and Processed Meat. Neutral: Alcohol; - DASH: Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy. Negative: Red and Processed Meat; Sweetened Beverages; Sodium; - GDQS, Positive: Vegetables (dark green leafy); Vegetables (Cruciferous); Vegetables (Deep Orange); Vegetables (Other); Tubers (Deep Orange); Fruit (Citrus); Fruit (Deep Orange); Fruit (Other); Legumes; Nuts and Seeds; Whole Grains; Fish and Shellfish; Poultry and Game; Low-fat Dairy; Eggs; Oils (Liquid). Negative: Processed meat; Refined grains and baked goods; Sweets and ice cream; SSBs; Juice; White roots and tubers; Purchased deep fried foods; Neutral (Moderate): High-fat Dairy; Red meat; - hGDQS (not clearly reported, 16 “healthy” items of GDQS): Positive: Vegetables (dark green leafy); Vegetables (Cruciferous); Vegetables (Deep Orange); Vegetables (Other); Tubers (Deep Orange); Fruit (Citrus); Fruit (Deep Orange); Fruit (Other); Legumes; Nuts and Seeds; Whole Grains; Fish and Shellfish; Poultry and Game; Low-fat Dairy; Eggs; Oils (Liquid).; - uGDQS (not clearly reported, 9 “unhealthy” items of GDQS): Negative: Processed meat; Refined grains and baked goods; Sweets and ice cream; SSBs; Juice; White roots and tubers; Purchased deep fried foods; Neutral (Moderate): High-fat Dairy; Red meat; - PDI: Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Negative: Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; - hPDI: Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Negative: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; - uPDI: Negative: Whole grains; Fruits; Vegetables; Nuts; Legumes; Vegetable oils; Tea/coffee; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; Positive: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; - EDIH, Positive: Red meat; Processed meat; Poultry; Tomatoes; French fries, Fish (non-dark); Low-fat dairy; Eggs; High-energy beverages (cola and other carbonated beverages with sugar, fruit drinks); Low-energy beverages; Butter/Margarine; Cream soups; Negative: Green leafy vegetables; Whole fruit; High-fat dairy products; Coffee; Wine; - EDIP, (reverse coded), Positive (Anti-Inflammatory): Vegetables (dark yellow: carrots, or squash), Vegetables (leafy green: cabbage, spinach, lettuce); Fruit juice (apple, cantaloupe, orange, or other fruit juice); Pizza; Snacks (cracker, potato chips); Tea; Coffee; Beer; Wine. Negative (Pro-Inflammatory): Vegetables, other (mixed, green pepper, cooked mushroom, eggplant, zucchini, or cucumber); Processed meat (sausage); Red meat (beef, or lamb); Organ meat (beef, calf, or chicken liver), Fish, canned tuna; Refined grains (white bread, biscuit, white rice, pasta, or vermicelli); High- and low-energy beverages (cola with sugar, carbonated beverages with sugar, fruit punch drinks); Tomatoes; DP Method(s): Index/Score Analysis; Comparisons: Continuous for each DP | Follow-Up Duration: 24y, median; Results for Overall CRC:; adj. for BMI; pooled ♀ + ♂ between DP & overall CRC risk (95% CI); sex-specific estimates by cohort were NS; WCRF-diet & overall CRC, HR: 0.91 (0.83, 1.00); p=0.06; CRC & overall CRC, HR: 0.95 (0.87, 1.05); p=0.31; Prudent & overall CRC, HR: 0.94 (0.86, 1.03); p=0.16; AHEI-2010 & overall CRC, HR: 0.99 (0.90, 1.09); p=0.83; aMED & overall CRC, HR: 0.96 (0.87, 1.06); p=0.41; DASH & overall CRC, HR: 0.87 (0.79, 0.95); p=0.004; GDQS & overall CRC, HR: 0.95 (0.86, 1.04); p=0.23; hGDQS & overall CRC, HR: 0.97 (0.88, 1.06); p=0.47; uGDQS & overall CRC, HR: 0.94 (0.86, 1.02); p=0.15; PDI & overall CRC, HR: 1.03 (0.94, 1.13); p=0.52; hPDI & overall CRC, HR: 0.94 (0.85, 1.03); p=0.16; uPDI & overall CRC, HR: 1.09 (0.99, 1.19); p=0.07; Western & overall CRC, HR: 1.13 (1.03, 1.23); p=0.008; EDIH & overall CRC, HR: 1.14 (1.04, 1.24); p=0.006; EDIP & overall CRC, HR: 1.18 (1.08, 1.29); p=0.0002; Summary: NS/Inverse: Prudent DP & overall CRC, Proximal colon, Distal Colon, Rectal Cx; NS/Inverse: AHEI-2010 & overall CRC, Proximal colon, Distal Colon, Rectal Cx; NS/Inverse: aMED & overall CRC, Proximal colon, Distal Colon, Rectal Cx; Inverse: DASH & overall CRC, Proximal colon, Distal Colon, Rectal Cx; NS/Inverse: GDQS & overall CRC, Proximal colon, Distal Colon, Rectal Cx; NS/Inverse: hGDQS & overall CRC, Proximal colon, Distal Colon, Rectal Cx; NS/Inverse: uGDQS & overall CRC, Proximal colon, Distal Colon, Rectal Cx; NS/Inverse: PDI & overall CRC, Proximal colon, Distal Colon, Rectal Cx; NS/Inverse: hPDI & overall CRC, Proximal colon, Distal Colon, Rectal Cx; Positive/NS: uPDI & overall CRC, Proximal colon, Distal Colon, Rectal Cx; Positive: Western DP & overall CRC, Proximal colon, Distal Colon, Rectal Cx; Positive: EDIH & overall CRC, Proximal colon, Distal Colon, Rectal Cx; Positive: EDIP & overall CRC, Proximal colon, Distal Colon, Rectal Cx | - Did not account for: Race/Ethnicity (“predominantly White”), SEP (all health professionals), Screening (Hx); - Diet assessment: FFQ every 4y; - Outcome measurement: Incident cases determined by self-report, NDI; Tumor location and Dz stage from medical records & study physician; - n= 3428 CRC cases (1420 proximal colon; 931 distal colon; 720 rectal); - Funding: NIH
Wang, 2022_Healthy^23^; United States; NHS; HPFS; Analytic N=123773; Participant characteristics:; - [underlined: Health]: BMI, mean: 25.1-26.3 (Q4-Q1, PDI); - Smoker: 4-15% current; 23-28% current HRT use; - [underlined: Race and/or Ethnicity]: Predominantly White; - [underlined: SEP]: NR (all health professionals); [underlined: Selection:] Excluded those with or who had: implausible/extreme TEI; missing birth year; Dx of Cx or colitis/IBD; missing tissue/data for molecular analyses | DP Age(s): 48-54y, mean (range: 30 to 75y at baseline); DP(s) examined: Plant-Based Diet Index (PDI) - healthful (hPDI)/unhealthful PDI (uPDI) [Satija, 2016]; DP Components:; - hPDI: Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Negative: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; - uPDI: Negative: Whole grains; Fruits; Vegetables; Nuts; Legumes; Vegetable oils; Tea/coffee; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; Positive: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; DP Method(s): Index/Score Analysis; Comparisons: Continuous and Categorical, by quartiles (Q1, HR: 1 REF) | Follow-Up Duration: NR; ~30y; Results for Overall CRC:; hPDI & overall CRC; pooled ♀ + ♂ (95% CI); Q2, HR: 0.88 (0.79, 0.97); Q3, HR: 0.93 (0.83, 1.03); Q4, HR: 0.86 (0.77, 0.96); p=0.04; uPDI & overall CRC; pooled ♀ + ♂ (95% CI); Q2, HR: 1.07 (0.96, 1.18); Q3, HR: 1.08 (0.97, 1.2); Q4, HR: 1.16 (1.04, 1.29); p=0.005; Summary: Inverse: hPDI & overall CRC (NS: Q3); Positive: uPDI & overall CRC (NS: Q2, Q3) | - Did not account for: Race/Ethnicity (“predominantly White”), SEP (all health professionals), Screening (Hx); - Diet assessment: FFQ every 4y; - Outcome measurement: Incident cases determined by self-report, NDI; Tumor location and Dz stage from medical records & study physician; - n= 3077 CRC cases (1304 proximal colon; 853 distal colon; 636 rectal); - Funding: NIH; Cancer Research UK Grand Challenge Award
Wang, 2022_Association^24^; United States; NHS; HPFS; Analytic N=206248; Participant characteristics:; - [underlined: Health]: BMI, mean: 24.3-25.8; - Smoker: 9-26% current; ~31% current HRT use (NHSI+II); - [underlined: Race and/or Ethnicity]: 89-98% White; - [underlined: SEP]: NR (all health professionals); [underlined: Selection:] Excluded those with or who had: implausible/extreme TEI; Dx of Cx or colitis/IBD; missing data | DP Age(s): 52-55y, mean (range: 30 to 75y at baseline); DP(s) examined: UPF, Nova Classification System Group 4 [Monteiro, 2019]; DP Components:; - UPF, Nova4 (Fig. 1 top sources): Breads and breakfast foods 27% ♂, 25% ♀; Fats, condiments/sauces 22% ♂ or ♀; Sweet, snacks, desserts 17% ♂, 18% ♀; Beverages 13% ♂, 17% ♀; Meat, poultry or seafood based products 5% ♂, 3% ♀; Ready-to-eat or heat mixed dishes 5% ♂, 4% ♀; Yogurt and dairy based desserts 5% ♂, 4% ♀; Savory snacks 4% ♂ or ♀; Other 2% ♂, 3% ♀; DP Method(s): Index/Score Analysis; Comparisons: Categorical and linear-trend by energy-adjusted serv/d quartiles (Q1, HR: 1 REF) | Follow-Up Duration: 24-28y; Results for Overall CRC:; Nova 4/UPF & overall CRC (95% CI); ♂, Q2, HR: 1.20 (1.01, 1.43); ♂, Q3, HR: 1.02 (0.85, 1.22); ♂, Q4, HR: 1.13 (0.95, 1.35); ♂, Q5, HR: 1.24 (1.04, 1.48); p-trend=0.02; ♀, Q2, HR: 0.89 (0.77, 1.03); ♀, Q3, HR: 0.94 (0.82, 1.09); ♀, Q4, HR: 0.97 (0.84, 1.12); ♀, Q5, HR: 1.01 (0.88, 1.17) ; p-trend=0.87; Summary: Positive: UPF/Nova4 (Q5 vs. Q1) in ♂ & overall CRC; Proximal Colon; Distal Colon; NS/Null: data in ♀; other quartiles; UPF/Nova4 & Rectum Cx in ♂ or ♀ | - Did not account for: SEP (all health professionals), Screening (Hx); - Diet assessment: FFQ every 4y; - Outcome measurement: Incident cases determined by self-report, NDI; Tumor location and Dz stage from medical records & study physician; - n= 3216 CRC cases (1304 proximal colon; 853 distal colon; 636 rectal); - Funding: NIH/NIMHD; Tufts University
Willemsen, 2022^26^; Canada; Alberta’s Tomorrow Project; Analytic N=26242; Participant characteristics:; - [underlined: Health]: BMI, mean: 29.7-32.6 (66% OW/Ob, with BMI > 25); - Smokers: 33-47% never; - [underlined: Race and/or Ethnicity]: NR(“homogenous; Canadian”); - [underlined: SEP]: Majority cohabitating/married (~72-84%) and employed FT (~35-78%); Income: ~23-46% low, 35-49% mid, 15-32% highest category; [underlined: Selection:] Excluded those with or who: missing data/unreliable diet; Hx of Cx | DP Age(s): 51y, mean at baseline; DP(s) examined: “Western” DP; “Prudent” DP; “Dietary fiber” DP; “Vitamin D” DP; “Fruits, sugar and dairy” DP; DP Components:; - “Western” DP: Grains (non-whole), vegetables, white potatoes, cheese, red and processed meats, discretionary fats, and added teaspoons of sugar.; - “Prudent” DP: Vegetables, fruits, and lean meat from fish and other seafood; - “Dietary fiber” DP: Grain servings, vegetables, and fruits; - “Vitamin D” DP: Dairy, fish, and other seafood; - “Fruits, sugar and dairy” DP: Whole grains, fruits, dairy, and teaspoons of added sugar; DP Method(s): RRR; Factor/Cluster Analysis: PCA; Comparisons: Categorical and linear-trend by quartiles (Q1, HR: 1 REF) | Follow-Up Duration: 13.3y, mean; Results for Overall CRC:; Summary: NS/Null: “Western” DP & Colon Cx; Inverse/NS: “Prudent” DP (Q2 only) & Colon Cx; Inverse: “Dietary fiber” DP (Q3, Q4) & Colon Cx; NS/Null: “Vitamin D” DP & Colon Cx; NS/Null: “Fruits, sugar and dairy” DP & Colon Cx | - Did not account for: Race/Ethnicity, SEP, Screening, Alcohol, Postmenopausal hormone therapy; - Diet assessment: FFQ; - Outcome measurement: Incident cases identified via registry linkage and/or medical records; - Cases identified: n= 543 (BCx); n= 199 (Colon Cx); - Funding: Alberta Health and the Alberta Cancer Prevention Legacy Fund, Alberta Cancer Foundation, Canadian Partnership Against Cancer, Alberta Health Services
Xiao, 2023^27^; United States; Prostate, Lung, Colorectal, and Ovarian (PLCO) Cancer Screening Trial; Analytic N=72721; Participant characteristics:; - [underlined: Health]: BMI, mean: 27 (SD: 5); - 6% Hx of DM; Smokers: 49% never; - [underlined: Race and/or Ethnicity]: 94% White; 6% Non-White; - [underlined: SEP]: Education: 28% high-school or less; 73% some college/degree; [underlined: Selection:] Excluded those with or who: missing baseline questionnaire/data (BMI, PA, Smoking); invalid FFQ; missing 8+ FFQ items; Hx of Cx; implausible/extreme TEI | DP Age(s): 65y (SD: 6) (range: 55 to 74y at baseline); DP(s) examined: Paleolithic Diet Score [Whalen 2014]; DP Components:; - Paleo, Positive: Vegetables; Fruit and Vegetable Diversity; Fruit; Nuts; Fish; Lean Meat; Calcium (from non-dairy foods). Negative: Grains and Starches; Baked Goods; Red and Processed Meat; Dairy Foods; Alcohol; Sodium; DP Method(s): Index/Score Analysis; Comparisons: Categorical and linear-trend by quartiles (Q1, HR: 1 REF) | Follow-Up Duration: 9.2y, mean; Results for Overall CRC:; Paleo & overall CRC; Q2, HR: 0.88 (0.71, 1.09); Q3, HR: 0.79 (0.64, 0.97); Q4, HR: 0.76 (0.61, 0.95); p-trend=0.009,; Summary: Inverse: Paleolithic diet score & overall CRC, proximal colon Cx; NS/Inverse: Distal CRC | - Did not account for: Screening; - Diet assessment: FFQ; - Outcome measurement: Incident cases identified via self-report, medical records a/o NDI; confirmed via medical records/pathology via physician; - Cases identified: n=694 CRC (420 proximal colon; 272 distal CRC; 2 unknown site); - Funding: The General Project of Chongqing Natural Science Foundation, Chongqing Science and Technology Commission, China; Kuanren Talents Project of the Second Afliated Hospital of Chongqing Medical University in China
Yue, 2021^28^; United States; NHS II; Analytic N=94217; Participant characteristics:; - [underlined: Health]: BMI, mean: 26.4; - 4% Hx DM; Smoker: 35% ever; 39% postmenopausal; - [underlined: Race and/or Ethnicity]: 93% White; - [underlined: SEP]: NR (all health professionals); [underlined: Selection:] Excluded those with or who had: implausible/extreme TEI; Dx of Cx or colitis/IBD; missing data | DP Age(s): 46.7y, mean (range, 25 to 42y at baseline); DP(s) examined: Prime (aka Global) Diet Quality score (GDQS) [Fung, 2018]; Plant-Based Diet Index (PDI) - healthful (hPDI)/unhealthful PDI (uPDI) [Satija, 2016]; Empirical Dietary Indices for Hyperinsulinaemia (EDIH) [Tabung, 2016]; DP Components:; - PDQS, Positive: Vegetables (dark green leafy); Vegetables (Cruciferous); Vegetables (Deep Orange); Vegetables (Other); Tubers (Deep Orange); Fruit (Citrus); Fruit (Deep Orange); Fruit (Other); Legumes; Nuts and Seeds; Whole Grains; Fish and Shellfish; Poultry and Game; Low-fat Dairy; Eggs; Oils (Liquid). Negative: Processed meat; Refined grains and baked goods; Sweets and ice cream; SSBs; Juice; White roots and tubers; Purchased deep fried foods; Neutral (Moderate): High-fat Dairy; Red meat; - PDI: Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Negative: Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; - hPDI: Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Negative: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; - uPDI: Negative: Whole grains; Fruits; Vegetables; Nuts; Legumes; Vegetable oils; Tea/coffee; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; Positive: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; - EDIH, Positive: Red meat; Processed meat; Poultry; Tomatoes; French fries, Fish (non-dark); Low-fat dairy; Eggs; High-energy beverages (cola and other carbonated beverages with sugar, fruit drinks); Low-energy beverages; Butter/Margarine; Cream soups; Negative: Green leafy vegetables; Whole fruit; High-fat dairy products; Coffee; Wine; DP Method(s): Index/Score Analysis; Comparisons: Categorical and linear-trend per each DP by quartiles (Q1, HR: 1 REF) | Follow-Up Duration: 24y (2,11,655 person-years F/U); Results for Overall CRC:; PDQS & CRC; Q2, HR: 0.81 (0.60, 1.11); Q3, HR: 0.96 (0.71, 1.30); Q4, HR: 0.80 (0.57, 1.11); p-trend=0.29; cont. 75th %-tile, HR: 0.91 (0.67, 1.24); PDI & CRC; Q2, HR: 1.25 (0.91, 1.72); Q3, HR: 1.45 (1.05, 2.00); Q4, HR: 1.16 (0.81, 1.67); p-trend=0.28; cont. 75th %-tile, HR: 1.14 (0.82, 1.59); hPDI & CRC; Q2, HR: 0.95 (0.69, 1.30); Q3, HR: 0.95 (0.69, 1.31); Q4, HR: 0.92 (0.65, 1.28); p-trend=0.63; cont. 75th %-tile, HR: 0.91 (0.66, 1.25); uPDI & CRC; Q2, HR: 0.93 (0.69, 1.26); Q3, HR: 0.86 (0.62, 1.18); Q4, HR: 0.89 (0.63, 1.24); p-trend=0.42; cont. 75th %-tile, HR: 0.91 (0.66, 1.26); EDIH & CRC; Q2, HR: 1.38 (0.99, 1.92); Q3, HR: 1.46 (1.04, 2.06); Q4, HR: 1.67 (1.15, 2.44); p-trend=0.01; cont. 75th %-tile, HR: 1.41 (0.99, 2.01); Summary: NS/Inverse: PDQS & overall CRC; NS/Null: Proximal colon; Distal colon; Rectum; Distal colon and rectum; NS/Null: PDI & overall CRC, Proximal colon; Distal colon; Rectum; Distal colon and rectum Positive: EDIH (Q3, Q4) & overall CRC; NS/Null: Proximal colon; Distal colon; Rectum; Distal colon and rectum | - Did not account for: SEP, Screening; - Diet assessment: FFQ every 4y; - Outcome measurement: Incident cases determined by self-report, NDI; Tumor location and Dz stage from medical records & study physician; - n= 332 CRC cases ( proximal colon; distal colon; rectal); - Funding: NIH
Zhang, 2021^29^; Denmark; Danish Diet, Cancer and Health cohort (DCH); Analytic N=55744; Participant characteristics:; - [underlined: Health]: BMI: OW 42%, Ob 15%; - Smokers: 35% never; HRT: 28% never, 16% current; - [underlined: Race and/or Ethnicity]: NR (Danish); - [underlined: SEP]: Education: 15% none, 23% short, 40% medium, 22% high; [underlined: Selection:] Excluded those with or who: missing relevant data (diet, background, smoking, alcohol, Cx); Dx/Hx of Cx | DP Age(s): 56y, median; 50-64 y at baseline; DP(s) examined: Dutch Dietary Guidelines - 2015 [Kromhout, 2016]; DP Components:; - DDG, Positive: Vegetables; Legumes; Fruit; Nuts, unsalted; Whole Grains; Fish; Liquid cooking fats, Vegetable Oils, Soft Margarine; Tea. Negative: Red and Processed Meat; Sugar-Sweetened Beverages; Alcohol; DP Method(s): Index/Score Analysis; Comparisons: Categorical and linear trend for DDGI by quartiles (Q1, HR: 1 REF) | Follow-Up Duration: 18.9y, median; Results for Overall CRC:; DDGI & CRC; Q2, HR: 0.91 (0.80, 1.04); Q3, HR: 0.80 (0.69, 0.92); Q4, HR: 0.66 (0.53, 0.84); p-trend<0.001; Summary: Inverse: DDGI & CRC; Colon Cx; NS: Rectal Cx | - Did not account for: Race/Ethnicity (Danish), Screening; - Diet assessment: FFQ; - Outcome measurement: Incident cases identified via linkage to cancer/death registry; CX defined by ICD codes; - Cases identified: n=1879 CRC (n=1256 colon; n=623 rectal); - Funding: None reported

a Abbreviations: BMI: body mass index; CRC: colorectal cancer; Cx: cancer; DP: dietary pattern; DM: diabetes mellitus; Dx: diagnosis; FFQ: food frequency questionnaire; HR: hazard ratio; HTN: hypertension; HRT: hormone replacement therapy; Hx: history of; NDI: national death index; NR: not reported; NS: not statistically significant; OB: obesity; OR: odds ratio; OW: overweight; PA: physical activity; REF: referent group; SEP: socioeconomic position; TEI: total energy intake;

Table 7 Risk of bias for observational studies examining dietary pattern consumption by adults and older adults and colorectal cancer^a^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Arima, 2022^1^ | HIGH | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Arthur, 2023^2^ | SOME CONCERNS | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Barrubés, 2020^3^ | HIGH | LOW | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | HIGH
Castelló, 2022^4^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Chaltiel, 2022^5^ | HIGH | LOW | LOW | LOW | SOME CONCERNS | LOW | LOW | HIGH
Chang, 2023^6^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Chebet, 2020^7^ | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | LOW | LOW | LOW | HIGH
Hoang, 2023^8^ | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS | HIGH
Jin, 2023^9^ | LOW | SOME CONCERNS | LOW | SOME CONCERNS | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Kim, 2022^10^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Kim, 2023^11^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS | HIGH
Lee, 2023^12^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | HIGH
Liu, 2023^13^ | HIGH | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Maimaitiyiming, 2023^14^ | SOME CONCERNS | LOW | LOW | LOW | HIGH | SOME CONCERNS | SOME CONCERNS | HIGH
Moazzen, 2022^15^ | HIGH | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | HIGH
Neuhouser, 2022^16^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | HIGH
Nguyen, 2020^17^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Petermann-Rocha, 2021^18^ | HIGH | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | HIGH
Ren, 2023^19^ | HIGH | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | LOW | HIGH
Schulpen, 2020^20^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Shang, 2023^21^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | LOW | LOW | SOME CONCERNS
Thompson, 2023^22^ | SOME CONCERNS | LOW | LOW | LOW | LOW | LOW | HIGH | HIGH
Wang, 2022^24^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | HIGH
Wang, 2022^23^ | HIGH | SOME CONCERNS | LOW | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | HIGH
Wang, 2023^25^ | HIGH | SOME CONCERNS | LOW | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | HIGH
Willemsen, 2022^26^ | VERY HIGH | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | HIGH | VERY HIGH
Xiao, 2023^27^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS
Yue, 2021^28^ | HIGH | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS | HIGH
Zhang, 2021^29^ | HIGH | SOME CONCERNS | LOW | LOW | LOW | LOW | LOW | HIGH

a Possible ratings of low, some concerns, high, very high, no information, or not applicable were determined using the “Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)” tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602. ) *Low risk of bias except for concerns about uncontrolled confounding.