# Plain language summary

### What is the question?

The question is: What is the relationship between dietary patterns consumed and risk of colorectal cancer? The populations of interest for this question included infants, young children, children, adolescents, adults, and older adults.

### Why was this question asked?

This systematic review was conducted by the 2025 Dietary Guidelines Advisory Committee as part of the process to develop the Dietary Guidelines for Americans, 2025-2030.

### How was this question answered?

The Committee conducted a systematic review to answer this question with support from the USDA Nutrition Evidence Systematic Review team. This review updated an existing review that was conducted by the 2020 Dietary Guidelines Advisory Committee.

### What is the answer to the question?

Dietary patterns consumed by adults and older adults that are characterized by higher intakes of vegetables, fruits, legumes and nuts, and whole grains, and lower intakes of red and processed meats, refined grains, fried potatoes, saturated fat, and sugar-sweetened foods and beverages are associated with lower risk of colon and rectal cancer. Some of these dietary patterns also included fish, low-fat dairy, tea and coffee. This conclusion statement is based on evidence graded as moderate.

### How up-to-date is this systematic review?

Conclusion statements from this review are based on articles published between January 2000 and January 2024.