# Appendix 5 Excluded articles

The following table lists the articles excluded after full-text screening for this systematic review question. At least one reason for exclusion is provided for each article, though this may not reflect all possible reasons. Information about articles excluded after title and abstract screening is available upon request.

Table A 4 List of Excluded articles with rationale

Number | Citation | Rationale
1 | Aguilera-Buenosvinos I, Martínez-González MÁ, Zazpe I, Romanos-Nanclares A, Sánchez-Bayona R, Toledo E. Associations between overall, healthful, and unhealthful low-fat dietary patterns and breast cancer risk in a Mediterranean cohort: The SUN project. Nutrition. 2023.109:111967. doi:10.1016/j.nut.2022.111967. | Intervention/Exposure
2 | Aroke, D, Folefac, E, Shi, N, et al. Inflammatory and Insulinemic Dietary Patterns: Influence on Circulating Biomarkers and Prostate Cancer Risk. Cancer Prev Res (Phila). 2020. 13:841-852. doi:10.1158/1940-6207.Capr-20-0236. | Outcome
3 | Blackie K, Bobe G, Takata Y. Vegetarian diets and risk of all-cause mortality in a population-based prospective study in the United States. J Health Popul Nutr. 2023. 42(1):130. doi:10.1186/s41043-023-00460-9. | Intervention/Exposure
4 | Botteri, E, Peveri, G, Berstad, P, et al. Changes in Lifestyle and Risk of Colorectal Cancer in the European Prospective Investigation Into Cancer and Nutrition. Am J Gastroenterol. 2023. 118(4):702-711. doi:10.14309/ajg.0000000000002065. | Intervention/Exposure
5 | Cai, H, Sobue, T, Kitamura, T, et al. Low-carbohydrate diet and risk of cancer incidence: The Japan Public Health Center-based prospective study. Cancer Science. 2022. 113:744-755. doi:10.1111/cas.15215. | Intervention/Exposure
6 | Castelló, A, Rodríguez-Barranco, M, Lope, V, et al. High adherence to Western dietary pattern increases breast cancer risk (an EPIC-Spain study). Maturitas. 2024. 179:107868. doi:10.1016/j.maturitas.2023.107868. | Outcome
7 | Castelló A, Rodríguez-Barranco M, Pérez-Gómez B, Chirlaque MD, Bonet C, Amiano P, et al. High adherence to Western dietary pattern and prostate cancer risk: findings from the EPIC-Spain cohort. BJU Int. 2023. 132(3):272-282. doi:10.1111/bju.16001. | Outcome
8 | Chang, K, Millett, C, Rauber, F, et al. Ultra-processed food consumption, cancer risk, and cancer mortality: a prospective cohort study of the UK Biobank. EClinicalMedicine. 2023. 56:101840. doi:10.1016/j.eclinm.2023.101840. | Publication Status
9 | Chlebowski, RT, Aragaki, AK, Anderson, GL, et al. Dietary Modification and Breast Cancer Mortality: long-Term Follow-Up of the Women’s Health Initiative Randomized Trial. Journal of clinical oncology. 2020. 38:1419-1428. doi:10.1200/JCO.19.00435. | Outcome
10 | Chen, SLF, Braaten, T, Borch, KB, et al. Combined lifestyle behaviors and the incidence of common cancer types in the norwegian women and cancer study (Nowac). Clinical Epidemiology. 2021. 13:721-734. doi:10.2147/CLEP.S312864. | Intervention/Exposure
11 | Debras, C, Chazelas, E, Srour, B, et al. Fermentable Oligosaccharides, Disaccharides, Monosaccharides, and Polyols (FODMAPs) and Cancer Risk in the Prospective NutriNet-Santé Cohort. J Nutr. 2022. 152:1059-1069. doi:10.1093/jn/nxab379. | Intervention/Exposure
12 | Dela Cruz, R, Park, SY, Shvetsov, YB, et at. Diet Quality and Breast Cancer Incidence in the Multiethnic Cohort. Eur J Clin Nutr. 2020. 74:1743-1747. doi:10.1038/s41430-020-0627-2. | Outcome
13 | Fraser, GE, Cosgrove, CM, Mashchak, AD, et al. Lower rates of cancer and all-cause mortality in an Adventist cohort compared with a US Census population. Cancer. 2020. 126:1102-1111. doi:10.1002/cncr.32571. | Intervention/Exposure
14 | Fu, BC, Tabung, FK, Pernar, CH, et al. Insulinemic and Inflammatory Dietary Patterns and Risk of Prostate Cancer. Eur Urol. 2021. 79:405-412. doi:10.1016/j.eururo.2020.12.030. | Outcome
15 | Gardeazabal, I, Romanos-Nanclares, A, Martínez-González, MÁ, et al. Mediterranean dietary pattern is associated with lower incidence of premenopausal breast cancer in the Seguimiento Universidad de Navarra (SUN) Project. Public Health Nutr. 2020. 23:3148-3159. doi:10.1017/s1368980019003835. | Outcome
16 | Huang MC, Huang TT, Feng HC, Chen IC, Chang CI, Wang TN, et al. Lifestyle Factors and Energy Intakes with Risks of Breast Cancer among Pre- and Post- Menopausal Women in Taiwan. Nutrients. 2023. 15(18):3900. doi: 10.3390/nu15183900. | Study Design
17 | Jacobs, I, Taljaard-Krugell, C, Wicks, M, et al. Dietary Patterns and Breast Cancer Risk in Black Urban South African Women: The SABC Study. Nutrients. 2021. 13(11):4106. doi:10.3390/nu13114106. | Study Design
18 | Kliemann N, Rauber F, Bertazzi Levy R, Viallon V, Vamos EP, Cordova R, et al. Food processing and cancer risk in Europe: results from the prospective EPIC cohort study. Lancet Planet Health. 2023. 7(3):e219-e232. doi:10.1016/S2542-5196(23)00021-9. | Intervention/Exposure
19 | Kresovich, JK, Park, Y-MM, Keller, JA, et al. Healthy eating patterns and epigenetic measures of biological age. Am J Clin Nutr. 2022. 115(1):171-179. doi:10.1093/ajcn/nqab307. | Study Design; Outcome
20 | Lan, T, Park, Y, Colditz, GA, et al. Adolescent dietary patterns in relation to later prostate cancer risk and mortality in the NIH-AARP Diet and Health Study. Br J Cancer. 2023. 128(1):57-62. doi:10.1038/s41416-022-02035-7. | Outcome
21 | Leach, HJ, Baxter, BA, Beale, MN, et al. Feasibility of Beans/Bran Enriching Nutritional Eating For Intestinal Health & Cancer Including Activity for Longevity: A Pilot Trial to Improve Healthy Lifestyles among Individuals at High Risk for Colorectal Cancer. Integr Cancer Ther. 2020. 19:1534735420967101. doi:10.1177/1534735420967101. | Outcome
22 | Lécuyer, L, Dalle, C, Lefevre-Arbogast, S, et al. Diet-Related Metabolomic Signature of Long-Term Breast Cancer Risk Using Penalized Regression: An Exploratory Study in the SU.VI.MAX Cohort. Cancer Epidemiol Biomarkers Prev. 2020. 29:396-405. doi:10.1158/1055-9965.Epi-19-0900. | Study Design; Intervention/Exposure
23 | Loeb, S, Fu, BC, Bauer, SR, et al. Association of plant-based diet index with prostate cancer risk. Am J Clin Nutr. 2022. 115:662-670. doi:10.1093/ajcn/nqab365. | Outcome
24 | Long, M, Wang, W, Sun, Q. A high-fat diet: an unexpected role in preventing the metastatic seeding of colorectal cancer. Signal Transduct Target Ther. 2020. 5(1):257. 2020. doi:10.1038/s41392-020-00386-2. | Study Design
25 | Lopez-Pentecost, M, Crane, TE, Garcia, DO, et al. Role of dietary patterns and acculturation in cancer risk and mortality among postmenopausal Hispanic women: results from the Women’s Health Initiative (WHI). Journal of Public Health (Germany). 2022. 30:811-822. doi:10.1007/s10389-020-01342-8. | Outcome
26 | Männistö, S, Harald, K, Härkänen, T, et al. Association between overall diet quality and postmenopausal breast cancer risk in five Finnish cohort studies. Sci Rep. 2021. 11:16718. doi:10.1038/s41598-021-95773-2. | Outcome
27 | Myneni, AA, Giovino, GA, Millen, AE, et al. Indices of Diet Quality and Risk of Lung Cancer in the Women’s Health Initiative Observational Study. J Nutr. 2021. 151:1618-1627. doi:10.1093/jn/nxab033. | Outcome
28 | Nepal, S, Aslani, Z, Shi, N, et al. Associations of Dietary Patterns with Colorectal Adenomas in the Prostate, Lung, Colorectal, and Ovarian Cancer Cohort. Cancer Epidemiol Biomarkers Prev. 2023. 32(9):1260-1264. doi:10.1158/1055-9965.EPI-23-0143. | Outcome
29 | Nguyen, LH, Cao, Y, Hur, J, et al. The Sulfur Microbial Diet Is Associated With Increased Risk of Early-Onset Colorectal Cancer Precursors. Gastroenterology. 2021. 161:1423-1432.e4. doi:10.1053/j.gastro.2021.07.008. | Outcome
30 | O’Hearn, M, Erndt-Marino, J, Gerber, S, et al. Validation of Food Compass with a healthy diet, cardiometabolic health, and mortality among U.S. adults, 1999–2018. Nat Commun. 2022. 13(1):7066. doi:10.1038/s41467-022-34195-8. | Study Design
31 | Pan, K, Aragaki, AK, Neuhouser, ML, et al. Low-fat dietary pattern and breast cancer mortality by metabolic syndrome components: a secondary analysis of the Women’s Health Initiative (WHI) randomised trial. Br J Cancer. 2021. 125:372-379. doi:10.1038/s41416-021-01379-w. | Outcome
32 | Park, SY, Boushey, CJ, Shvetsov, YB, et al. Diet Quality and Risk of Lung Cancer in the Multiethnic Cohort Study. Nutrients. 2021. 13. doi:10.3390/nu13051614. | Outcome
33 | Park, YM, Shivappa, N, Petimar, J, et al. Dietary inflammatory potential, oxidative balance score, and risk of breast cancer: Findings from the Sister Study. Int J Cancer. 2021. 149:615-626. doi:10.1002/ijc.33581. | Intervention/Exposure; Outcome
34 | Peila, R, Arthur, RS, Dannenberg, AJ, Rohan, TE. Association of a Healthy Lifestyle Index with Risk of Breast Cancer among Women with Normal Body Mass Index in the UK Biobank. Cancer Epidemiol Biomarkers Prev. 2022. 31:554-560. doi:10.1158/10559965.Epi-21-0765. | Outcome
35 | Peila, R, Chlebowski, R, Manson, JA, et al. Low-fat dietary modification and risk of ductal carcinoma in situ of the breast in the women’s health initiative dietary modification trial. Cancer Epidemiology Biomarkers and Prevention. 2021. 30:1753-1756. doi:10.1158/1055-9965.EPI-21-0404. | Outcome
36 | Peila, R, Lane, DS, Shadyab, AH, et al. Healthy lifestyle index and the risk of ductal carcinoma in situ of the breast in the Women’s Health Initiative. Int J Cancer. 2022. 151:526-538. doi:10.1002/ijc.34034. | Intervention/Exposure;
37 | Plym, A, Zhang, Y, Stopsack, KH, et al. A Healthy Lifestyle in Men at Increased Genetic Risk for Prostate Cancer. Eur Urol. 2022. doi:10.1016/j.eururo.2022.05.008. | Outcome
38 | Rassy, N, Van Straaten, A, Carette, C, et al. Association of Healthy Lifestyle Factors and Obesity-Related Diseases in Adults in the UK. JAMA Network Open. 2023. 6:E2314741. | Intervention/Exposure
39 | Romanos-Nanclares, A, Tabung, FK, Willett, WC, et al. Insulinemic potential of diet and risk of total and subtypes of breast cancer among US females. Am J Clin Nutr. 2022. doi:10.1093/ajcn/nqac284. | Intervention/Exposure
40 | Romanos-Nanclares, A, Toledo, E, Sánchez-Bayona, R, Sánchez-Quesada, C, Martínez-González, MÁ, Gea, A. Healthful and unhealthful provegetarian food patterns and the incidence of breast cancer: Results from a Mediterranean cohort. Nutrition. 2020. 79-80:110884. doi:10.1016/j.nut.2020.110884. | Outcome
41 | Romanos-Nanclares, A, Willett, WC, Rosner, BA, et al. Healthful and Unhealthful Plant-Based Diets and Risk of Breast Cancer in U.S. Women: Results from the Nurses’ Health Studies. Cancer Epidemiol Biomarkers Prev. 2021. 30:1921-1931. doi:10.1158/10559965.Epi-21-0352. | Outcome
42 | Sciacca S, Lo Giudice A, Asmundo MG, Cimino S, Morgia G, Alshatwi AA, et al. Adherence to Healthy or Unhealthy Pro-Vegetarian Plant-Based Diets Have Different Impact on Prostate Cancer Severity: Preliminary Findings. Nutr Cancer. 2024. 76(1):98-105. doi:10.1080/01635581.2023.2279240. | Outcome
43 | Shah, S, Mahamat-Saleh, Y, Ait-Hadad, W, et al. Long-term adherence to healthful and unhealthful plant-based diets and breast cancer risk overall and by hormone receptor and histologic subtypes among postmenopausal females. Am J Clin Nutr. 2023. 117(3):467-476. doi:10.1016/j.ajcnut.2022.11.019. | Study Design; Outcome
44 | Shah S, Mahamat-Saleh Y, Hajji-Louati M, et al. Palaeolithic diet score and risk of breast cancer among postmenopausal women overall and by hormone receptor and histologic subtypes. Eur J Clin Nutr. 2023. 77(5):596-602. doi:10.1038/s41430-023-01267-x | Outcome
45 | Shin, WK, Lee, HW, Shin, A, et al. Multi-Grain Rice Diet Decreases Risk of Breast Cancer in Korean Women: Results from the Health Examinees Study. Nutrients. 2020. 12(8)doi:10.3390/nu12082273. | Outcome
46 | Shin, S, Saito, E, Sawada, N, et al. Dietary patterns and colorectal cancer risk in middle-aged adults: A large population-based prospective cohort study. Clin Nutr. 2018. 37(3):1019-1026. doi:10.1016/j.clnu.2017.04.015. | Outcome
47 | Shin, S, Saito, E, Sawada, N, et al. Dietary patterns and prostate cancer risk in Japanese: the Japan Public Health Center-based Prospective Study (JPHC Study). Cancer Causes Control. 2018. 29(6):589-600. doi:10.1007/s10552-018-1030-3. | Publication Date Outcome
48 | Sieri, S, Agnoli, C, Pala, V, et al. Dietary Intakes of Animal and Plant Proteins and Risk of Colorectal Cancer: The EPIC-Italy Cohort. Cancers (Basel). 2022. 14. doi:10.3390/cancers14122917. | Intervention/Exposure
49 | Thordardottir, GS, Einarsdottir, K, Thordardottir, M, et al. Dietary patterns in adolescence and risk of colorectal cancer: a population-based study. Cancer Causes Control. 2022. 33:205-211. doi:10.1007/s10552-021-01524-z. | Intervention/Exposure; Age: Intervention/Exposure
50 | Ugai, T, Liu, L, Tabung, FK, et al. Prognostic role of inflammatory diets in colorectal cancer overall and in strata of tumor-infiltrating lymphocyte levels. Clin Transl Med. 2022. 12(11):e1114. doi:10.1002/ctm2.1114. | Health Status
51 | van den Brandt PA. The association of a combined healthy lifestyle with the risk of postmenopausal breast cancer subtypes in the Netherlands Cohort Study. Eur J Epidemiol. Jun 2023;38(6):629-641. doi:10.1007/s10654-023-01005-4. | Outcome
52 | Vitellius, C, Bertrais, S, Antier, J, et al. Evaluation of a risk score based on dietary and lifestyle factors to target a population at risk in colorectal cancer screening. Digestive and Liver Disease. 2021. 53:900-907. doi:10.1016/j.dld.2021.03.008. | Study Design; Intervention/Exposure
53 | Wang, Q, Hashemian, M, Sepanlou, SG, et al. Dietary quality using four dietary indices and lung cancer risk: the Golestan Cohort Study (GCS). Cancer Causes Control. 2021. 32:493-503. doi:10.1007/s10552-021-01400-w. | Outcome
54 | Wang, W, Fung, TT, Wang, M, et al. Association of the Insulinemic Potential of Diet and Lifestyle With Risk of Digestive System Cancers in Men and Women. JNCI Cancer Spectr. 2018. 2(4):pky080. doi:10.1093/jncics/pky080 | Intervention/Exposure
55 | Wang, Y, Nguyen, LH, Mehta, RS, et al. Association Between the Sulfur Microbial Diet and Risk of Colorectal Cancer. JAMA Netw Open. 2021. 4(11):e2134308. doi:10.1001/jamanetworkopen.2021.34308. | Intervention/Exposure
56 | Watling, CZ, Schmidt, JA, Dunneram, Y, et al. Risk of cancer in regular and low meat-eaters, fish-eaters, and vegetarians: a prospective analysis of UK Biobank participants. BMC Med. 2022. 20:73. doi:10.1186/s12916-022-02256-w. | Intervention/Exposure
57 | Wei, X, Zhu, C, Ji, M, et al. Diet and Risk of Incident Lung Cancer: A Large Prospective Cohort Study in UK Biobank. Am J Clin Nutr. 2021. 114:2043-2051. doi:10.1093/ajcn/nqab298. | Outcome
58 | Xiao Y, He H, Xiang L, Gu H, Xu Z, Luo H, et al. Association between sulfur microbial diet and the risk of colorectal cancer precursors in older adults. Front Nutr. 2023. 10:1167372. doi:10.3389/fnut.2023.1167372. | Outcome
59 | Yiannakou I, Singer MR, Moore LL. Indices of Mediterranean diet adherence and breast cancer risk in a community-based cohort. Front Nutr. 2023;10:1148075. doi:10.3389/fnut.2023.1148075 | Outcome
60 | Yu YC, Paragomi P, Jin A, Wang R, Schoen RE, Koh WP, et al. Low-Carbohydrate Diet Score and the Risk of Colorectal Cancer: Findings from the Singapore Chinese Health Study. Cancer Epi Biom Prev. 2023. 32(6):802-808.doi:10.1158/1055-9965.EPI-22-0683 | Intervention/Exposure
61 | Zhang, J, Yu, H, Huang, T, et al. Importance of ideal cardiovascular health metrics in the risk of colorectal cancer among people aged 50 years or older: a UK Biobank cohort study. BMJ Open. 2022. 12:e059642. doi:10.1136/bmjopen-2021-059642. | Comparator
62 | Zhang, Y, Zhong, G, Zhu, M, et al. Association Between Diabetes Risk Reduction Diet and Lung Cancer Risk in 98,159 Participants: Results From a Prospective Study. Front Oncol. 2022. 12:855101. doi:10.3389/fonc.2022.855101. | Outcome
63 | Zhang, YB, Pan, XF, Lu, Q, et al. Associations of combined healthy lifestyles with cancer morbidity and mortality among individuals with diabetes: results from five cohort studies in the USA, the UK and China. Diabetologia. 2022. doi:10.1007/s00125-022-05754-x. | Intervention/Exposure; Health Status
64 | Zhang, Z, Tabung, FK, Jin, Q, et al. Diet-Driven Inflammation and Insulinemia and Risk of Interval Breast Cancer. Nutr Cancer. 2022. 74:3179-3193. doi:10.1080/01635581.2022.2063350. | Outcome
65 | Zhu P, Zhang Y, Chen Q, et al. The interaction of diet, alcohol, genetic predisposition, and the risk of breast cancer: a cohort study from the UK Biobank. Eur J Nutr. Mar 2024;63(2):343-356. doi:10.1007/s00394-023-03269-8 | Outcome