# Appendix 3 Inclusion and exclusion criteria comparison between existing^*^ * Boushey C, Ard J, Bazzano L, Heymsfield S, Mayer-Davis E, Sabaté J, Snetselaar L, Van Horn L, Schneeman B, English LK, Bates M, Callahan E, Butera G, Terry N, Obbagy J. Dietary Patterns and Breast, Colorectal, Lung, and Prostate Cancer: A Systematic Review. July 2020. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: 10.52570/NESR.DGAC2020.SR0104 and updated systematic reviews

Table A 3 Inclusion and exclusion criteria comparison between existing^*^ and updated systematic reviews for the research question: What is the relationship between dietary patterns and risk of colorectal cancer?

Category | Existing Review | Updated Review | Change and Rationale
Study design | [underlined: Included]:; - Randomized controlled trials; - Non-randomized controlled trials, including quasiexperimental and controlled before and after studies; - Prospective cohort studies; - Retrospective cohort studies; - Nested case-control studies; [underlined: Excluded]:; - Uncontrolled trials^†^; † Including uncontrolled before-and-after studies; - Case-control studies; - Cross-sectional studies; - Narrative reviews; - Systematic reviews; - Meta-analyses | [underlined: Included]:; - Randomized controlled trials; - Non-randomized controlled trials; - Prospective cohort studies; - Retrospective cohort studies; - Nested case-control studies; [underlined: Excluded]:; - Uncontrolled trials; - Case-control studies; - Cross-sectional studies; - Ecological studies; - Narrative reviews; - Systematic reviews; - Meta-analyses; - Modeling and simulation studies; - Mendelian randomization studies | No change
Publication date | [underlined: Included]:; - January 2014 – January 2020 (this date range is in addition to the original systematic review, which included articles published from January 2000 – January 2014); [underlined: Excluded]:; - Articles published prior to January 2000 or after January 2020 | [underlined: Included]:; - January 2000 – January 2024 (this date range is encompassing the original systematic reviews, which included articles published from January 2000 – January 2020); [underlined: Excluded]:; - Articles published prior to January 2000 or after January 2024 | No change other than to include more recent evidence
Population: Study participants | [underlined: Included]:; - Human participants; - Males; - Females; [underlined: Excluded]:; - Non-human participants (e.g. animal or in vitro models) | [underlined: Included]:; - Human; [underlined: Excluded]:; - Non-human | No change other than formatting
Population: Life stage | [underlined: Included]:; - Age at intervention/exposure:; ○ Children and adolescents (ages 2-18; ○ years); ○ Adults (ages 19-64 years); ○ Older adults (ages 65 years and older; - Age at outcome:; ○ Children and adolescents (ages 2-18; ○ years); ○ Adults (ages 19-64 years); ○ Older adults (ages 65 years and older); [underlined: Excluded]:; - Age at intervention/exposure and outcome:; ○ Infants and toddlers (birth up to 24 months); - At outcome:; ○ Infants and toddlers (birth up to 24 months) | [underlined: Included]:; - At intervention or exposure and outcome:; ○ Infants and young children (birth up to 24 months); ○ Children and adolescents (2 up to 19 years); ○ Adults and older adults (19 years and older); [underlined: Excluded]:; - At intervention or exposure and outcome:; ○ N/A; - At outcome:; ○ Individuals during pregnancy | Infants and young children (birth up to 24 months) will be included to focus the reviews on the entire lifespan.; Individuals where the outcome is diagnosed during pregnancy will be excluded due to the special nature of this life stage.
Population: Health Status | [underlined: Included]:; - Studies that enroll participants who are healthy and/or at risk for chronic disease, including those with obesity; - Studies that enroll some participants diagnosed with a disease; - Studies that enroll some participants diagnosed with cancer; [underlined: Excluded]:; - Studies that exclusively enroll participants diagnosed with a disease, or hospitalized patients with illness or injury. (For this criterion, studies that exclusively enroll subjects with obesity will be included.); - Studies that exclusively enroll participants with cancer (i.e., studies that aim to treat participants who have already been diagnosed with the outcome of interest) | [underlined: Included]:; - Studies that exclusively enroll participants not diagnosed with a disease; - Studies that enroll some participants:; ○ diagnosed with a disease;; ○ with severe undernutrition, failure to thrive/underweight, stunting, or wasting;; ○ born preterm, with low birth weight, and/or small for gestational age;; ○ pre- or post-bariatric surgery;; ○ receiving pharmacotherapy to treat obesity;; ○ and/or with the outcome of interest; [underlined: Excluded]:; - Studies that exclusively enroll participants:; ○ diagnosed with a disease;; ○ hospitalized for an illness, injury, or surgery;; ○ with severe undernutrition, failure to thrive/underweight, stunting, or wasting;; ○ born preterm,† with low birth weight,‡ and/or small for gestational age; ○ pre- or post-bariatric surgery;; ○ receiving pharmacotherapy to treat obesity;; ○ and/or with the outcome of interest | No change other than to clarify intent
Intervention/exposure | [underlined: Included]:; - Studies that examine consumption of and/or adherence to a dietary pattern [i.e., the quantities, proportions, variety, or combination of different foods, drinks, and nutrients (when available) in diets, and the frequency with which they are habitually consumed], including, at a minimum, a description of the foods and beverages in the pattern.; - Dietary patterns may be measured or derived using a variety of approaches, such as adherence to a priori patterns (indices/scores), data driven patterns (factor or cluster analysis), reduced rank regression, or other methods, including clinical trials.; [underlined: Excluded]:; - Studies that do not provide a description of the dietary pattern, which at minimum, must include the foods and beverages in the pattern (i.e., studies that examine a labeled dietary pattern, but do not describe the foods and beverages consumed). | [underlined: Included]:; - Studies that examine consumption of and/or adherence to a dietary pattern [i.e., the quantities, proportions, variety, or combination of different foods, drinks, and nutrients (when available) in diets, and the frequency with which they are habitually consumed], including, at a minimum, a description of the foods and beverages in the pattern of each intervention/exposure and comparator group; - Dietary patterns may be measured or derived using a variety of approaches, such as adherence to a priori patterns (indices/scores), data driven patterns (factor or cluster analysis), reduced rank regression, or other methods, including clinical trials; - Multi-component intervention in which the isolated effect of the dietary pattern on the outcome(s) of interest is provided or can be determined; [underlined: Excluded]:; - Studies that do not provide a description of the dietary pattern, which at minimum, must include the foods and beverages in the pattern (i.e., studies that examine a labeled dietary pattern, but do not describe the foods and beverages consumed in each intervention/exposure and comparator group); - Multi-component intervention in which the isolated effect of the dietary pattern on the outcome(s) of interest is not analyzed or cannot be determined (e.g., due to multiple intervention components within groups) | No change other than formatting to clarify intent of the criteria.
Comparator | [underlined: Included]:; - Consumption of and/or adherence to a different dietary pattern; - Different levels of consumption of and/or adherence to a dietary pattern; [underlined: Excluded]:; - N/A | [underlined: Included]:; - Consumption of and/or adherence to a different dietary pattern; - Different levels of consumption of and/or adherence to a dietary pattern; [underlined: Excluded:]; - Consumption of and/or adherence to a similar dietary pattern of which only a specific component or food source s differs between groups | No change other than formatting
Outcome(s) | [underlined: Included]; - Incident cases of:; ○ Breast cancer; ○ Colorectal cancer; ○ Lung cancer; ○ Prostate cancer; [underlined: Excluded]; - Studies that exclusively examine cancer-related mortality, prevalence, survivorship, or recurrence of cancer | [underlined: Included]; - Incident cases of colorectal cancer; [underlined: Excluded]; - Studies that exclusively examine cancer-related mortality, prevalence, survivorship, or recurrence of cancer | Specific cancer types were separated into different questions for clarity of reporting
Confounders | [underlined: Included]; - n/a; [underlined: Excluded]; - n/a | [underlined: Included]; - Studies that control for at least one of the key confounders listed in the analytic framework; [underlined: Excluded]; - Studies that control for at least one of the key confounders listed in the analytic framework | Criteria were added to enable focus on a stronger body of evidence
Study duration | [underlined: Included]; - N/A; [underlined: Excluded]; - N/A | [underlined: Included]; - Intervention study length ≥12 weeks; [underlined: Excluded]; - Intervention study length <12 weeks | Study duration criteria were modified to enable focus on the strongest body of evidence
Publication status | [underlined: Included]; - Articles that have been peer-reviewed; [underlined: Excluded]; - Articles that have not been peer-reviewed and are not published in peer-reviewed journals, including unpublished data, manuscripts, reports, abstracts, and conference proceedings | [underlined: Included]; - Peer-reviewed articles published in research journals; [underlined: Excluded]; ○ Non-peer reviewed articles, unpublished data or manuscripts, pre-prints, reports, and conference abstracts or proceedings | No change other than formatting
Language | [underlined: Included]; - Articles published in English; [underlined: Excluded]; - Articles published in languages other than English | [underlined: Included]; - Published in English; [underlined: Excluded]; - Not published in English | No change other than formatting
Country^*^; * The classification of countries on the Human Development Index (HDI) is based on the UN Development Program Human Development Report Office (http://hdr.undp.org/en/data) for the year the study intervention occurred or data were collected. If the study does not report the year(s) in which the intervention/exposure data were collected, the HDI classification for the year of publication is applied. Studies conducted prior to 1990 are classified based on 1990 HDI classifications. If the year is more recent than the available HDI values, then the most recent HDI classifications are used. If a country is not listed in the HDI, then the current country classification from the World Bank is used (The World Bank. World Bank country and lending groups. Available from: https://datahelpdesk.worldbank.org/knowledgebase/articles/906519-world-country-and-lending-groups) | [underlined: Included]; - Studies conducted in countries classified as high or very high on the Human Development Index the year(s) the intervention/exposure data were collected; [underlined: Excluded]; - Studies conducted in countries classified as medium or low on the Human Development Index the year(s) the intervention/exposure data were collected | [underlined: Included]; - Studies conducted in countries classified as high or very high on the Human Development Index the year(s) the intervention/exposure data were collected; [underlined: Excluded]; - Studies conducted in countries classified as medium or low on the Human Development Index the year(s) the intervention/exposure data were collected | No change