# Appendix 2 Conclusion statements from the existing^*^ * Boushey C, Ard J, Bazzano L, Heymsfield S, Mayer-Davis E, Sabaté J, Snetselaar L, Van Horn L, Schneeman B, English LK, Bates M, Callahan E, Butera G, Terry N, Obbagy J. Dietary Patterns and Breast, Colorectal, Lung, and Prostate Cancer: A Systematic Review. July 2020. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: 10.52570/NESR.DGAC2020.SR0104 systematic reviews for the research question: What is the relationship between dietary patterns consumption and risk of colorectal cancer?

Table A 2 Inclusion and exclusion criteria comparison between existing^*^ and updated systematic reviews for the research question: What is the relationship between dietary patterns and risk of colorectal cancer?

Citation | Conclusion statement and grade
2015 Dietary Guidelines Advisory Committee: Systematic Reviews of the Dietary Patterns, Foods and Nutrients, and Health Outcomes Subcommittee. February 2015. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: https://nesr.usda.gov/sites/default/files/201904/2015DGAC-SR-DietaryPatterns.pdf | Moderate evidence indicates an inverse association between dietary patterns that are higher in vegetables, fruits, legumes, whole grains, lean meats and seafood, low-fat dairy and moderate alcohol; and low in red and processed meats, saturated fat and sodas and sweets relative to other dietary patterns and the risk of colon and rectal cancer. Conversely, diets that are higher in red and processed meats, French fries and potatoes, and sources of sugars (i.e., sodas, sweets and dessert foods) are associated with a greater colon and rectal cancer risk. (Grade: Moderate)
Boushey C, Ard J, Bazzano L, Heymsfield S, Mayer-Davis E, Sabaté J, Snetselaar L, Van Horn L, Schneeman B, English LK, Bates M, Callahan E, Butera G, Terry N, Obbagy J. Dietary Patterns and Breast, Colorectal, Lung, and Prostate Cancer: A Systematic Review. July 2020. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: 10.52570/NESR.DGAC2020.SR0104 | Moderate evidence indicates that dietary patterns higher in vegetables, fruits, legumes, whole grains, lean meats and seafood, and low-fat dairy; and low in red and processed meats, saturated fat and sugar-sweetened beverages and sweets relative to other dietary patterns are associated with lower risk of colon and rectal cancer. Moderate evidence also indicates that dietary patterns that are higher in red and processed meats, French fries, potatoes, and sources of sugars (e.g., sugarsweetened beverages, sweets and dessert foods) are associated with a greater colon and rectal cancer risk. (Grade: Moderate).