# Appendix 1 Abbreviations

Table A 1 List of abbreviations

Abbreviation | Full name
DP | Dietary Pattern
FFQ | Food frequency questionnaire
HDI | Human Development Index
HEI | Healthy Eating Index
HHS | United States Department of Health and Human Services
NCC | Nested case-control study
NESR | Nutrition Evidence Systematic Review
NIH | National Institutes of Health
PCS | Prospective cohort study
RCT | Randomized controlled trial
SEP | Socioeconomic position
USDA | United States Department of Agriculture