# References of the articles included in the systematic review

1 Arthur RS, Wang T, Xue X, Kamensky V, Rohan TE. Genetic Factors, Adherence to Healthy Lifestyle Behavior, and Risk of Invasive Breast Cancer Among Women in the UK Biobank. J Natl Cancer Inst. Sep 1 2020;112(9):893–901. doi:10.1093/jnci/djz241 31899501
2 Castello A, Rodriguez-Barranco M, Lope V, High adherence to Western dietary pattern increases breast cancer risk (an EPIC-Spain study). Maturitas. Jan 2024;179:107868. doi:10.1016/j.maturitas.2023.107868 37925868
3 Chaltiel D, Julia C, Chaltiel R, Prospective association between adherence to the 2017 French dietary guidelines and risk of death, CVD and cancer in the NutriNet-Sante cohort. Br J Nutr. Feb 28 2022;127(4):619–629. doi:10.1017/S0007114521001367 34016201
4 Chang K, Gunter MJ, Rauber F, Ultra-processed food consumption, cancer risk and cancer mortality: a large-scale prospective analysis within the UK Biobank. EClinicalMedicine. Feb 2023;56:101840. doi:10.1016/j.eclinm.2023.101840 36880051
5 Chebet JJ, Thomson CA, Kohler LN, Association of Diet Quality and Physical Activity on Obesity-Related Cancer Risk and Mortality in Black Women: Results from the Women's Health Initiative. Cancer Epidemiol Biomarkers Prev. Mar 2020;29(3):591–598. doi:10.1158/1055-9965.EPI-19-1063 31915146
6 Chlebowski RT, Aragaki AK, Anderson GL, Dietary Modification and Breast Cancer Mortality: Long-Term Follow-Up of the Women's Health Initiative Randomized Trial. J Clin Oncol. May 1 2020;38(13):1419–1428. doi:10.1200/JCO.19.00435 32031879
7 Dela Cruz R, Park SY, Shvetsov YB, Diet Quality and Breast Cancer Incidence in the Multiethnic Cohort. Eur J Clin Nutr. Dec 2020;74(12):1743–1747. doi:10.1038/s41430-020-0627-2 32286532
8 Gardeazabal I, Romanos-Nanclares A, Martinez-Gonzalez MA, Mediterranean dietary pattern is associated with lower incidence of premenopausal breast cancer in the Seguimiento Universidad de Navarra (SUN) Project. Public Health Nutr. Dec 2020;23(17):3148–3159. doi:10.1017/S1368980019003835 32090723
9 Jin Q, Shi N, Lee DH, Hyperinsulinemic and Pro-Inflammatory Dietary Patterns and Metabolomic Profiles Are Associated with Increased Risk of Total and Site-Specific Cancers among Postmenopausal Women. Cancers (Basel). Mar 14 2023;15(6)doi:10.3390/cancers15061756
10 Maimaitiyiming M, Yang H, Zhou L, Zhang X, Cai Q, Wang Y. Associations between an obesity-related dietary pattern and incidence of overall and site-specific cancers: a prospective cohort study. BMC Med. Jul 10 2023;21(1):251. doi:10.1186/s12916-023-02955-y 37424008
11 Mannisto S, Harald K, Harkanen T, Association between overall diet quality and postmenopausal breast cancer risk in five Finnish cohort studies. Sci Rep. Aug 18 2021;11(1):16718. doi:10.1038/s41598-021-95773-2
12 Neuhouser ML, Pettinger M, Tinker LF, Associations of Biomarker-Calibrated Healthy Eating Index-2010 Scores with Chronic Disease Risk and Their Dependency on Energy Intake and Body Mass Index in Postmenopausal Women. J Nutr. Jan 14 2023;152(12):2808–2817. doi:10.1093/jn/nxac199 36040344
13 Peila R, Arthur RS, Dannenberg AJ, Rohan TE. Association of a Healthy Lifestyle Index with Risk of Breast Cancer among Women with Normal Body Mass Index in the UK Biobank. Cancer Epidemiol Biomarkers Prev. Mar 1 2022;31(3):554–560. doi:10.1158/1055-9965.EPI-21-0765 34933955
14 Petermann-Rocha F, Ho FK, Foster H, Nonlinear Associations Between Cumulative Dietary Risk Factors and Cardiovascular Diseases, Cancer, and All-Cause Mortality: A Prospective Cohort Study From UK Biobank. Mayo Clin Proc. Sep 2021;96(9):2418–2431. doi:10.1016/j.mayocp.2021.01.036 34366141
15 Romanos-Nanclares A, Tabung FK, Willett WC, Insulinemic potential of diet and risk of total and subtypes of breast cancer among US females. Am J Clin Nutr. Dec 19 2022;116(6):1530–1539. doi:10.1093/ajcn/nqac284 36178066
16 Romanos-Nanclares A, Toledo E, Sanchez-Bayona R, Sanchez-Quesada C, Martinez-Gonzalez MA, Gea A. Healthful and unhealthful provegetarian food patterns and the incidence of breast cancer: Results from a Mediterranean cohort. Nutrition. Nov-Dec 2020;79–80:110884. doi:10.1016/j.nut.2020.110884
17 Romanos-Nanclares A, Willett WC, Rosner BA, Healthful and Unhealthful Plant-Based Diets and Risk of Breast Cancer in U.S. Women: Results from the Nurses' Health Studies. Cancer Epidemiol Biomarkers Prev. Oct 2021;30(10):1921–1931. doi:10.1158/1055-9965.EPI-21-0352 34289970
18 Shah S, Mahamat-Saleh Y, Ait-Hadad W, Long-term adherence to healthful and unhealthful plant-based diets and breast cancer risk overall and by hormone receptor and histologic subtypes among postmenopausal females. Am J Clin Nutr. Mar 2023;117(3):467–476. doi:10.1016/j.ajcnut.2022.11.019 36872016
19 Shah S, Mahamat-Saleh Y, Hajji-Louati M, Palaeolithic diet score and risk of breast cancer among postmenopausal women overall and by hormone receptor and histologic subtypes. Eur J Clin Nutr. May 2023;77(5):596–602. doi:10.1038/s41430-023-01267-x 36726032
20 Shang X, Liu J, Zhu Z, Healthy dietary patterns and the risk of individual chronic diseases in community-dwelling adults. Nat Commun. Oct 23 2023;14(1):6704. doi:10.1038/s41467-023-42523-9 37872218
21 Shin WK, Lee HW, Shin A, Multi-Grain Rice Diet Decreases Risk of Breast Cancer in Korean Women: Results from the Health Examinees Study. Nutrients. Jul 29 2020;12(8)doi:10.3390/nu12082273
22 Thompson AS, Tresserra-Rimbau A, Karavasiloglou N, Association of Healthful Plant-based Diet Adherence With Risk of Mortality and Major Chronic Diseases Among Adults in the UK. JAMA Netw Open. Mar 1 2023;6(3):e234714. doi:10.1001/jamanetworkopen.2023.4714 36976560
23 van den Brandt PA. The association of a combined healthy lifestyle with the risk of postmenopausal breast cancer subtypes in the Netherlands Cohort Study. Eur J Epidemiol. Jun 2023;38(6):629–641. doi:10.1007/s10654-023-01005-4 37169990
24 Willemsen RF, McNeil J, Heer E, Johnson ST, Friedenreich CM, Brenner DR. Dietary patterns with combined and site-specific cancer incidence in Alberta's Tomorrow Project cohort. Eur J Clin Nutr. Mar 2022;76(3):360–372. doi:10.1038/s41430-021-00958-7 34168294
25 Yiannakou I, Singer MR, Moore LL. Indices of Mediterranean diet adherence and breast cancer risk in a community-based cohort. Front Nutr. 2023;10:1148075. doi:10.3389/fnut.2023.1148075 37025613
26 Zhu P, Zhang Y, Chen Q, The interaction of diet, alcohol, genetic predisposition, and the risk of breast cancer: a cohort study from the UK Biobank. Eur J Nutr. Mar 2024;63(2):343–356. doi:10.1007/s00394-023-03269-8 37914956