# Results

## Literature search and screening results

Articles included in this systematic review were identified from literature searches conducted to identify all potentially relevant articles for the systematic review assessing the relationship between dietary patterns consumed and breast cancer^*^. The literature search (Appendix 4) yielded 1,436 search results after the removal of duplicates (see Figure 2). Dual-screening resulted in the exclusion of 982 titles, 360 abstracts, and 69 full-texts articles. Reasons for full-text exclusion are in Appendix 5. One additional article was identified from the manual search. The body of evidence for breast cancer includes 26 articles^1–26^ published since 2020. In addition, this review updates an existing review,^†^ which developed and graded a conclusion based on 52 articles.

* Hoelscher DM, Anderson CAM, Booth S, . Dietary Patterns and Risk of Breast Cancer: A Systematic Review. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review; 2025. 10.52570/NESR.DGAC2025.SR21

† Boushey C, Ard J, Bazzano L, Heymsfield S, Mayer-Davis E, Sabaté J, Snetselaar L, Van Horn L, Schneeman B, English LK, Bates M, Callahan E, Butera G, Terry N, Obbagy J. Dietary Patterns and Breast, Colorectal, Lung, and Prostate Cancer: A Systematic Review. July 2020. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: 10.52570/NESR.DGAC2020.SR0104

Figure 2 Literature search and screen flowchart

## Adults and older adults

The 2025 Dietary Guidelines Advisory Committee updated the existing systematic review by synthesizing the additional 26 articles that were published between January 2020 and January 2024 and met inclusion criteria, and assessing how this new evidence relates to the conclusion statement from the existing review.

Twenty-six articles met inclusion criteria examining the relationship between dietary patterns consumed and risk of breast cancer.^1–26^ Eighteen articles^1,2,4,5,8–13,15–19,22,23,25^ reported risk of postmenopausal breast cancer (Table 6) and 10 articles reported risk of premenopausal breast cancer (Table 7).^1,2,4,8,10,13,15–17,21^

### Description of the evidence

#### Population

Analytic sample size ranged from N=1,579^25^ up to N=422,702.^14^ Follow-up durations ranged between a median of 6.3^21^ years up to 32 years^15,17^.

The number of cases identified across the studies varied and ranged from 87 breast cancer cases from a cohort of 1,579^25^ to 18,768 breast cancer cases from a cohort of 112,468 participants,^9^ both with about 18 years of follow-up time.

Articles used data collected from a total of 8 countries with 13 articles using data collected in the United States:

- Nurses’ Health Study II (NHS),^15,17^ n=2
- Women’s Health Initiative (WHI),^5,12^ n=2
- WHI-Dietary Modification trial,^6,9^ n=2
- Multi-Ethnic cohort (MEC),^7^ n=1
- Framingham Offspring Study,^25^ n=1

Additional countries and cohorts were represented in the data as follows:

- United Kingdom, n=8 (UK Biobank)^1,4,10,13,14,20,22,26^
- Canada, n=1 (Alberta’s Tomorrow Project)^24^
- Finland, n=1 (Prospective Meta-Cohort Study of Cancer Burden in Finland (METCA project)),^11^
- Spain, n=3 (SUN,^8,16^ n=2; European Prospective Investigation into Cancer and Nutrition (EPIC)-Spain,^2^ n=1)
- Korea, n=1 (Health Examinees-Gem (HEXA-G) part of Korean Genome and Epidemiology Study (KoGES),^21^)
- France, n=3 (E3N,^18,19^ n=2; NutriNet-Santé,^3^ n=1)
- The Netherlands, n=1 (The Netherlands Cohort Study (NLCS)^23^)

##### Health status

Among 21 articles that reported mean BMI, 13 reported mean BMI was ≥ 25 kg/m^2^ (full range: 22.2 up to 32.6 kg/m^2^).^2,5,6,9–12,14,15,17,23–25^ Among 8 articles that reported BMI categories, all reported that ≥40% of the study participants had overweight and/or obesity.^4,5,7,9,14,22,24,26^

Twenty-three articles reported information on smoking, including never smoking ranged from <11 to 96% (n=17)^1,2,4–8,10,12–14,21–24,26^ or a current smoking range from 4 to 37% (n=6).^7,9,11,18–20^

Fourteen articles reported on HRT use: with current HRT use ranged from: 9 to 50% (n=9);^2,3,6,8,10,12,13,25,26^; Ever HRT use ranged from: 7 to 69% (n= 6);^4,7,11,15,23^ Eight articles reported family history of cancer or BC family. History of breast cancer: 6 to 15.5% (n= 6);^1,15–19^, family history of benign breast disease: 9 to 30% (n= 4);^15,17–19^; and family history of any cancer: 5 to 36% (n=2).^2,4^

##### Race and/or Ethnicity.

The reported race and/or ethnicity of study samples indicated homogeneity across the included articles. Fourteen articles reported that they included populations that were >77% White.^1,4,6,9,10,12–15,17,20,22,25,26^ Three included articles reported that <40% of the study population was White, one of which was 100% Korean;^21^ one was 100% Black;^5^ and the other reported about 13–30% "White", 16–26% "African-American", 16–29% "Native Hawaiian", 15–27% "Japanese American"; 11–26% "Latina".^7^ Nine of the articles did not report the race or ethnicity of their populations,^2,3,8,11,16,18,19,23,24^ and were conducted in the following populations: French,^3,18,19^ Spanish,^2,8,16^ Finnish,^11^, Dutch,^23^ or Canadian.^24^

##### Socioeconomic position (SEP).

Variability in participants’ SEP was demonstrated among the articles reporting such information. Five articles did not report an indication of socioeconomic position,^1,11,15,17,23^ however, 2 of those articles used data from populations of 100% health professionals.^15,17^ Education was the most commonly-reported indicator of socioeconomic position, but income, socioeconomic status (e.g. Townsend index), occupation status, and/or cohabitation status were also reported in XX articles. Populations with high education, employment status, or Townsend index were represented in 9 articles,^8,10,12,13,15–19^ low education or household income in 1 article,^2^ or mixed socioeconomic position in 13 articles represented by household income, education, occupation, or Townsend index.^3–7,9,14,20–22,24–26^

#### Intervention/Exposure and Comparator

Dietary patterns consumption was examined among participants whose mean ages ranged from about 34.5 years^8^ to 63.6 years.^12^ The majority of articles assessed dietary intake multiple times throughout the course of study, however 19 of those only used a single measure in their analysis.^1,2,5–9,11–14,16,17,21–26^ Nine articles only collected and used dietary data from a single collection at baseline.^1,2,7,8,16,21,23–25^ Therefore, the majority of analyses were based on a single measure of dietary intake. The most common diet assessment method used was FFQ (n=18),^1,5–9,11,12,15–21,23–25^ followed by 24-hour dietary recall (n=7),^3,4,10,13,14,22,26^ and diet history questionnaires (n=1).^2^

Dietary pattern methods included:

- Index/Score analysis: n=20^1,3–5,7,9,11–20,22,23,25,26^
- Factor/Cluster: n=3^2,8,21,24^
- Randomized Controlled Trial: n=1^6^
- Reduced Rank Regression: n=1^10^
- Factor/Cluster and Reduced Rank Regression: n=1^24^

A visualization of all dietary pattern components in each dietary pattern examined in relation to outcomes of interest is available in Appendix 6.

#### Outcomes

Methods used to assess incident cases of breast cancer varied across the articles. Fourteen articles identified cases using linkages to cancer, death, or health registries, medical or hospital records, or national health services.^1,2,4,7,11,13–15,20–24,26^ Nine articles initially identified cases using self-report, then confirmed cases using the national death index, medical records or pathology reports, health insurance and mortality registries.^3,5,6,8,9,12,16,17,25^ The remaining articles determined incident cases using questionnaires inquiring about cancer occurrence, contact details of physicians, and from insurance and death certificates, or confirmed by clinical and pathology reports, or did not report their methods.^10,18,19^

The majority of articles reported risk of postmenopausal breast cancer (35 comparisons from 18 articles).^1,2,4,5,8–13,15–19,22,23,25^. However, many articles reported overall risk of breast cancer either alone or as well as risk of pre or postmenopausal breast cancer.^2–4,7,8,14–17,20,24–26^ A smaller portion of articles reported risk of premenopausal breast cancer (19 comparisons from 10 articles).^1,2,4,8,10,13,15–17,21^

Of the articles that reported postmenopausal breast cancer, only 8 articles reported results by molecular subtypes.^2,9,15,17–19,23,25^ Subtypes were grouped such that all outcomes that included a single subtype marker, like estrogen-receptor positive (ER+) were considered together. If an article compared the same dietary pattern with multiple subtypes within the same grouping, they were checked for consistency in direction and significance of results but were only considered once. The groupings were as follows:

- ER+: 18 comparisons from 8 articles^2,9,15,17–19,23,25^
  ○ ER+,^9,15,17–19,23^
  ○ ER+/PR+,^18,19,23,25^
  ○ ER+/PR−,^23^
  ○ ER+/PR+/HER2−^2,9,15,17^
- Estrogen-receptor negative (ER−): 14 comparisons from 7 articles^2,9,15,17–19,23^
  ○ ER−,^9,15,17–19,23^
  ○ ER−/PR−,^18,19,23^
  ○ ER−/PR−/HER2+,^9,15,17^
  ○ ER−/PR−/HER2−^2,9^
- Progesterone-receptor positive (PR+): 18 comparisons from 8 articles^2,9,15,17–19,23,25^
  ○ PR+,^9,18,19,23^
  ○ ER+/PR+,^18,19,23,25^
  ○ ER+/PR+/HER2−^2,9,15,17^
- Progesterone-receptor negative (PR−): 14 comparisons from 7 articles^2,9,15,17–19,23^
  ○ PR−,^9,18,19,23^
  ○ ER+/PR−,^23^ ER−/PR−,^18,19,23^
  ○ ER−/PR−/HER2+,^9,15,17^
  ○ ER−/PR−/HER2−^2,9^
- Human epidermal growth factor receptor 2 (HER2+): 10 comparisons from 4 articles^2,9,15,17^
  ○ HER2+,^2,9^
  ○ ER−/PR−/HER2+,^9,15,17^,
  ○ Luminal B (ER+ and/or PR+/HER2+)^9,15,17^
- Human epidermal growth factor receptor 2 (HER2−): 10 comparisons from 4 articles^2,9,15,17^
  ○ HER2−,^9^
  ○ ER+/PR+/HER2−^2,9,15,17^
  ○ ER−/PR−/HER2−^2,9^

### Synthesis of the evidence

#### Postmenopausal breast cancer

Lower risk of postmenopausal breast cancer was associated with dietary patterns that reflected higher intakes of vegetables, fruits, legumes and nuts, and whole grains, and lower intakes of red and processed meats.^1,8,11,13,17–19,23,25^ Higher risk of postmenopausal breast cancer was associated with dietary patterns that reflected higher intakes of sugar-sweetened foods and beverages, and refined grains.^2,8–10,15–18,22^. When synthesized together and oriented as evidence for a relationship with lower risk of postmenopausal breast cancer, the patterns shared similar direction of findings and magnitude of effect estimates in 35 comparisons in 18 articles from observational studies.^1,2,4,5,8–13,15–19,22,23,25^ Statistically significant results were reported in 9 comparisons from 6 articles^2,9,15,17–19^ supported by 16 comparisons from 12 articles that were not statistically significant but reported results in a consistent direction.

Most of these dietary patterns included fish intake as a contributor to these dietary patterns (~24 of 35 dietary patterns examined), and while it was included as a positive component in many patterns associated with lower risk of postmenopausal breast cancer, it was also included as a positive component in many patterns that were associated with higher risk of postmenopausal breast cancer. Dairy and/or milk products were often included but considered differently across these dietary patterns, such as with total dairy and/or milk products scored as a negative component compared to specifically low-fat dairy scored positively. The methods and labels for these dietary patterns varied across the body of evidence, including a priori indices or scores such as “Mediterranean” style, dietary guideline-related, “Plant-based” diet scores, and other scores, as well as posteriori or hybrid methods (e.g., factor analysis and reduced rank regression) across observational studies.

- Dietary patterns derived from various indices/scores were used in the majority of the observational studies, which reported similar results despite variation in the name, label, or style of dietary pattern (e.g., Mediterranean, dietary guideline-related, “Plant-based”, or other).
  ○ “Mediterranean” style scores were associated with lower risk of postmenopausal breast cancer,^11,23,25^ Similarities across these “Mediterranean” indices included: scoring vegetables (not potatoes), fruit, legumes, nuts, whole grains, fish, and unsaturated vegetable oils/fats as positive components; alcoholic beverages as neutral components; and red and processed meat as negative components.
  ○ An association between dietary guideline-related scores and lower risk of postmenopausal breast cancer was not reported in the 4 articles.^5,9,11,12^ Similarities across these indices included vegetables, fruits, legumes and nuts, whole grains, and sources of unsaturated fats (relative to saturated fats) scored positively, and total protein, sources of saturated fats, added sugars (e.g., sugar-sweetened foods or beverages), and sodium each scored negatively. Several scores included total protein foods and seafood/plant proteins scored positively and refined grains negatively. Two articles using the HEI-2015,^5,9^ 1 article using the HEI-2010,^12^ 1 article using a modified Alternative HEI (AHEI) as well as a modified Nordic Diet score (mNDI) reported similar results.^11^
  “Plant-based” or plant-focused diet scores were associated with postmenopausal breast cancer, however the direction of the association depended on the framing of the dietary pattern.^16–18,22^ Across all “plant-based” patterns animal products were scored as negative, including fish and seafood, meats and meat products, eggs, dairy, animal-source fats and miscellaneous animal-based foods. Two articles using the Plant-based Dietary Index (PDI), which scores anything positively other than the animal-product components listed above, reported associations with lower risk of postmenopausal breast cancer.^17,18^ Two articles using the “healthful” version of the PDI, also reported associations in the same direction. This “healthful” PDI also scores fruit juices; sugar-sweetened beverages; refined grains; potatoes; sweets/desserts negatively. The “unhealthful” version of either the PDI or the Provegetarian Food Pattern (PVG) was associated with higher risk of postmenopausal breast cancer.^16–18,22^ In addition to animal-based products, the “unhealthful” plant-based patterns also scores vegetables, legumes, nuts, whole grains, vegetable oils, and tea and coffee negatively and scores potatoes, fruit juice, refined grains and sugar-sweetened foods and beverages positively. Two articles that used the “healthful” PDI or PVG reported no association with postmenopausal breast cancer.^16,22^
  ○ Other dietary pattern indices/scores were associated with risk of postmenopausal breast cancer but the direction of the association depended on the characteristics of the patterns. Scores associated with lower risk of postmenopausal breast cancer included WCRF/AICR related diet scores^1,13^ and a Paleolithic Score.^19^ These patterns were characterized by scoring vegetables, fruits, and whole grains positively and red and processed meats negatively. Scores associated with higher risk of postmenopausal breast cancer included empirical dietary indices for hyperinsulinaemia (EDIH)^9,15^ or a reverse-coded empirical dietary inflammatory pattern (EDIP).^9^ These patterns were characterized by lower vegetable, fruit or fruit juice, and tea or coffee and higher intakes of fish, red and processed meats, sugar-sweetened beverages. One article using the Nova classification system for “ultra-processed food (UPF)” reported no association with postmenopausal breast cancer.^4^
- Studies using other analytic approaches to identify dietary patterns aligned with the findings from investigator-derived dietary pattern indices/scores. Two similar posteriori patterns characterized with high consumption of vegetables, fruits, legumes, nuts, eggs, fish, natural fruit juices, processed and unprocessed red meat, poultry, olive oil, potatoes and other fruits reported one null association^2^ and one non-significant result in the direction of lower risk of postmenopausal breast cancer.^8^ Three similar patterns with lower whole grains, and higher in refined grains and red or processed meats reported results in the direction of higher postmenopausal breast cancer,^2,8,10^ one of which was statistically significant.^2^

When articles reported risk of overall breast cancer as well as risk of postmenopausal breast cancer, results were generally consistent in direction of the effect and in the dietary patterns assessed. There were 16 comparisons from 6 articles that only reported results for overall risk of breast cancer.^3,7,14,20,24,26^ The descriptive statistic and mean ages of participants indicated a mixture of both postmenopausal and premenopausal women included in these analyses. Nine dietary pattern comparisons were consistent with the findings for postmenopausal women as where an additional 7 comparisons from 3 articles reported null results^7,20,24^.

#### Premenopausal breast cancer

The data regarding dietary patterns and risk of premenopausal breast cancer point in the same direction as the results of the postmenopausal breast cancer data, however the evidence is less consistent in the dietary patterns and included food components, as well as the significance, direction, and magnitude of the results. This was supported by 19 comparisons from 10 articles of which 3 comparisons were statistically significant.^1,2,4,8,10,13,15–17,21^ Dietary patterns associated with lower premenopausal breast cancer tended to be higher in vegetables, fruits, legumes, nuts, whole grains, and lower in red and processed meats. Sugar-sweetened foods and beverages, fish and seafood, and refined grains were not consistently represented in the patterns.

The methods and labels for these dietary patterns varied across the body of evidence, including a priori indices or scores such as “plant-based” diet scores, WCRF/AICR-related scores, EDIH, or Nova, as well as posteriori or hybrid methods (e.g., factor analysis and reduced rank regression) across observational studies.

- Two WCRF/AICR-related diet scores,^1,13^ and 4 “plant-based” diets^16,17^ characterized by higher intakes of vegetables, fruits, whole grains, and lower intakes of meat (including red and processed meats) reported results associated with lower risk of premenopausal breast cancer. Only the WCFR/AICR-related scores were statistically significant.
- Three patterns reported non-significant results in the direction of higher risk of premenopausal breast cancer and were characterized by lower intakes of vegetables, fruits, and higher intakes of red and processed meats.^15–17^ One additional pattern that looked at ultra-processed foods using Nova classification also reported a non-significant finding in the same direction.^4^
- Posteriori or hybrid methods including factor analysis and reduced rank regression were used in 9 comparisons from 4 articles^2,8,10,21^ of which 2 were statistically significant.^8,21^ The patterns included in this group varied and were not able to be characterized together due to inconsistent inclusion of food components and differences in whether a food component was higher or lower across the patterns.

#### Molecular subtypes of postmenopausal breast cancer

Eighteen comparisons from 8 articles that assessed postmenopausal breast cancer also reported at least one result by molecular subtypes of the tumors.^2,9,15,17–19,23,25^ Tumors with ER+,^2,9,15,17–19,23,25^ ER−,^2,9,15,17–19,23^ PR+,^2,9,15,17–19,23,25^ PR−,−,^2,9,15,17–19,23^ molecular subtypes were generally consistent with the results reported for all postmenopausal breast cancers. This indicates that in the included data, the association between dietary patterns and postmenopausal breast cancer does not vary depending on ER or PR status. Results for HER2+ or HER2− tumors were slightly less consistent as compared with other molecular subtypes but were less frequently assessed and had less representation in included cases, leading to less certainty around effect estimates.^2,9,15,17^

Triple-negative tumors or those with an ER−/PR−/HER2− subtype were of specific interest due to their unique risk profile and higher prevalence in African American women. However, only 3 articles included participants with this tumor type and nothing additional could be attributed.^2,6,9^

### Conclusion statement and grade

The 2025 Dietary Guidelines Advisory Committee updated the existing conclusion statement^*^,^†^ (Appendix 2) to answer the question, “What is the relationship between dietary patterns consumed and risk of breast cancer?” based on their review of the body of evidence on adults and older adults from an additional 26 articles that met inclusion criteria and were published between January 2020 and January 2024 (Table 5).

* A conclusion statement is carefully constructed, based on the evidence reviewed, to answer the systematic review question. A conclusion statement does not draw implications and should not be interpreted as dietary guidance.

† Boushey C, Ard J, Bazzano L, Heymsfield S, Mayer-Davis E, Sabaté J, Snetselaar L, Van Horn L, Schneeman B, English LK, Bates M, Callahan E, Butera G, Terry N, Obbagy J. Dietary Patterns and Breast, Colorectal, Lung, and Prostate Cancer: A Systematic Review. July 2020. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: 10.52570/NESR.DGAC2020.SR0104

Table 5 Conclusion statement, grades for dietary patterns consumed by adults and older adults and risk of breast cancer

Conclusion Statement | Dietary patterns consumed by adults and older adults that are characterized by higher intakes of vegetables, fruits, legumes and nuts, and whole grains, and lower intakes of red and processed meats, refined grains, and sugar-sweetened foods and beverages are associated with lower risk of postmenopausal breast cancer relative to other dietary patterns. The data regarding dietary patterns and risk of premenopausal breast cancer point in the same direction, but the evidence is less consistent. This conclusion statement is based on postmenopausal breast cancer evidence graded as moderate. (Grade: Moderate)
Grade | Moderate
Body of Evidence | 26 articles (21 RCT; 24 PCS; 1 NCC) assessed as they relate to the evidence in the existing review^†^ (52 articles)
Consistency | Some concerns with variability in the magnitude of the results and few concerns with the variability in the direction of results.
Precision | Some concerns with studies reporting wider confidence intervals across effect estimates.
Risk of bias | Some concerns with higher risk of bias, primarily due to confounding, exposure only being measured one time, and selection of the reported results.
Directness | A few concerns with exposure, comparators, and outcomes being directly related to the systematic review question.
Generalizability | Serious concerns with generalizability to the U.S. population due to lack of diversity in race and/or ethnicity.

#### Assessment of the evidence

The body of evidence underlying the conclusion statement includes 26 articles published since 2020, were assessed as they relate to the evidence included in the existing review.^†^ Dietary patterns were assessed using various analytic approaches, including an investigator-assigned dietary intervention, index/score analysis, factor/cluster analysis, and reduced rank regression. Incident cases of breast cancer was determined from various methods including self-report, registry linkage, hospital records. As outlined and described below, the body of evidence was assessed for the following elements used when grading the strength of evidence. This body of evidence includes both large and small studies (with significant as well as null findings) so publication bias may be less likely.

##### Consistency

For postmenopausal breast cancer, the direction of the findings were consistent, however there were some concerns with the variability in the magnitude of the results as well and statistical significance of the findings. Effect estimates tended to be higher when confidence intervals were wider. While only 9 out of 35 comparisons were statistically significant, those were supported by 16 comparisons that did not reach statistical significance that were in a consistent direction with similar dietary patterns. For premenopausal breast cancer, results varied based on dietary patterns and food components included in the patterns across studies, but results trended in a similar direction.

##### Precision

There were some concerns that results across studies were not able to reach statistical significance, however this data was supported by the consistency of the direction of findings in non-statistically significant findings. There were a total of 26 articles, 25 of which were observational analyses. Sample sizes ranged from N=1,579 up to N=422,702 (most studies >50,000 participants). The number of ascertained cases corresponded to sample size, age of participants, and duration of follow-up. Results that did reach statistical significance were from studies with sample sizes of >50,000, baseline age of participants was ~50 years and duration of follow up was at least 17 years.

##### Risk of bias

There were numerous risks of bias across domains, which may influence the reported results (Table 8 and Table 9). Many of the studies did not account for breast cancer screening which was identified as a key confounder a priori. Many of the articles also may be at a higher risk of exposure classification due to only assessing dietary patterns at one time point and not accounting for potential diet changes over long periods of follow-up. Additionally, because many of the studies were observational, they didn’t have pre-specified analytic plans and therefore tended to be at higher risk of bias for selection of reported results.

##### Directness

Studies and/or analyses were designed to directly examine the relationship between dietary patterns and risk of breast cancer outcomes.

##### Generalizability

Socioeconomic positions of participants varied across included articles and were likely generalizable to the U.S. population, however, there were serious concerns with the generalizability of the racial and ethnic representation in the articles included in this review. Eight out of 26 studies were conducted in the U.S., however, the lack of diversity within most of those articles as well as those conducted outside of the U.S. leads to serious concerns with applicability to the U.S. population. Most of the articles that reported race and/or ethnicity reported that the majority of participants were White, and many studies conducted outside of the U.S. did not report racial and/or ethnic information. Most dietary patterns examined across studies are applicable to diets consumed by Americans. Additionally, measurement of dietary patterns in younger populations is needed to explore the critical window of exposure for the relationship between consumption of dietary patterns and both premenopausal and postmenopausal breast cancer. Participants across the body of evidence represented a range of health disparities based on studies that reported such information, including a majority of participants without chronic disease as well as those with overweight, obesity, and variable family history of cancer. Outcomes examined in the body of evidence, including overall risk of breast cancer, risk of breast cancer based on menopausal status, and by molecular subtypes, are relevant to the U.S. population of interest. However, less common molecular subtypes such as triple negative tumors (i.e., ER−/PR−/HER2−), that disproportionately impact those of African descent, were not able to be independently assessed because of too few studies.

## Research recommendations

- Examine populations that are generalizable to the U.S. population with regards to SEP and racial and/or ethnic groups.
- Adopt methodologic approaches for defining different dietary patterns such that patterns can be consistently identified, scored and compared across studies, including clearer description of foods and food components (e.g. low-fat dairy vs. dairy, red and processed meat vs total protein).
- Establish population studies starting earlier in life to better capture dietary patterns contributing to risk of breast cancer risk later in life. Important considerations would be addressing phases of the life cycle relevant to breast cancer, including childhood and menarche, adolescence and periods of mammary gland development and growth, periods of reproduction and lactation and subsequent years prior to cancer development.
  ○ Assess premenopausal breast cancer to determine if lack of consistency is reflective of a true relationship, or due to methodological concerns.
- Assess associations of dietary patterns by subtypes of breast cancer defined by histopathologic outcomes, tumor hormone receptor status, molecular genotypes, gene expression patterns and other biological characteristics that influence the tumor behavior, for example, by tumor hormone receptor status and other relevant phenotypic characteristics (e.g. HER2 status).
  ○ Specific need for more studies on triple negative breast cancer that is more likely to impact persons of African descent.
- Collect and include information on:
  ○ the confounding contribution of breast cancer screening when assessing the relationship between dietary patterns and breast cancer;
  ○ gender status in addition to sex;
  ○ additional information on all types of hormone therapy, in addition to postmenopausal hormone therapy.

Table 6 Evidence examining the relationship between dietary patterns consumed by adults and older adults and risk of postmenopausal breast cancer^a^

Article Information | Dietary pattern (DP) intervention/exposure and comparator | Postmenopausal Breast Cancer Results^*^; * All results are presented as the effect estimate (e.g., Hazard ratio, HR; Relative risk, RR) and 95% Confidence interval as (lower limit, upper limit) unless otherwise noted; Reference groups are the lowest dietary pattern category, HR: 1, unless otherwise noted | Methodological considerations
Arthur, 2020 ^1^; United Kingdom; UK BIOBANK; Analytic N=146326; Participant characteristics:; - Cases v. non-cases: BMI 18.5 to 24.9: 33% v. 39%; WC <80 cm: 32% v. 38%; - ~55–63% never smokers; - Family Hx breast Cx, 10 to 15.5%; - 100% European ancestry; - ~21% of participants in lowest quintle of Townsend deprivation index (similar across cases vs. noncases); Selection data: Excluded men, outliers for heterozygosity or missing genotype; discordant genotype vs. reported sex; putative sex chromosome aneuploidy; unknown tumor behavior; with Cx Hx; non-Eurpoean ancestry; underweight; missing lifestyle or genetic factors unknown menopausal status with no info on hysterectomy or oophorectomy | DP Age(s): 61 years (postmenopausal); 40–69 y at baseline; DP and DP Components: modified WCRF/AICR Score - Diet only [Shams-White, 2019], mWCRF/AICR, Positive: Fruits & Vegetables; Whole grains. Negative: Red meat; Processed meat; DP Method(s): Index/Score Analysis | Follow-up: 7.1 years (median); IQR 6.3–7.7; [underlined: Risk of Postmenopausal BCx]; mWCRF/AICR; 0 pts, HR: 1.00, ref; 1 pt, HR: 0.97 (0.89, 1.05; 2 pts, HR: 0.92 (0.82, 1.04); p-trend=0.18 | - Did not account for: None; - Diet assessment: FFQ at baseline; - Outcomes: Incident cases determined by linkage to national cancer registries in England, Wales, Scotland & death registries; - BCx cases, n=3422 (n=706 premenopausal; n=2716 postmenopausal); - Diet score is component of overall Healthy Lifestyle Index; - Funding: Breast Cancer Research Foundation
Castelló, 2024 ^2^; Spain; European Prospective Investigation into Cancer and Nutrition (EPIC)-Spain; Analytic N=24892; Participant characteristics:; - BMI, mean: 27.48;; - Smokers: 71% never; ~5% Family Hx of Cx; 9% HRT; - NR; - Education: 79% primary school or less/none (39% none, 40% primary, 11% secondary, 10% univesity+); Selection data: Excluded those with or who had: BMI of 60+; implausible/extreme TEI; first y of F/U; missing covariate data | DP Age(s):47.6 years (median) at entry (IQR: 41.2–54.8); DP and DP Components: “Western” DP: high intakes of high-fat dairy products, processed meat, refined grains, sweets, caloric drinks, convenience food and sauces [e.g., crackers, snacks, egg derivatives; processed white/blue fish]; Low intakes of low-fat dairy products and whole grains;; “Prudent” DP: high intakes of low-fat dairy products, vegetables, fruits, whole grains and [veg./fruit] juices; “Mediterranean” DP: high intakes of fish, vegetables, legumes [Peas, lentils, chickpeas, beans and broad beans], boiled potatoes, fruits, olives, and vegetable oil; Low intake of [veg./fruit] juices; DP Method(s): Factor/Cluster Analysis: PCA | Follow-up: 17.02 years, median; [underlined: Risk of Postmenopausal BCx]; Western DP; Q2, HR: 1.14 (0.89, 1.48); Q3, HR: 1.3 (0.98, 1.72); Q4, HR: 1.42 (1.04, 1.94); p-trend=0.021; per-SD, HR: 1.09 (0.97, 1.22); Prudent DP; Q2, HR: 1.12 (0.85, 1.46); Q3, HR: 1.14 (0.87, 1.5); Q4, HR: 1.12 (0.83, 1.49); p-trend=0.451; per-SD, HR: 1.08 (0.98, 1.2); Mediterranean DP; Q2, HR: 1.06 (0.83, 1.39); Q3, HR: 1.14 (0.88, 1.48); Q4, HR: 1.03 (0.075, 1.41); p-trend=0.623; per-SD, HR: 1.03 (0.93, 1.16) | - Did not account for: Race/Ethnicity, Screening, Postmenopausal hormone therapy (BC only); - Diet assessment: Diet Hx questionnaire; - Outcomes: Incident cases identified by cancer and registry linkage; definined by ICD via first occurrence of primary malignant tumor of the breast (Intrinsic sub-types classifed by pathology via ASCO/CAP guidelines: ER+, PR+, HER2−; HER2+ (irrespective of ER/PR); TN (triple negative, ER−, PR−, HER2−);; - n=639 cases BCx identified; - Intakes of dairy and fish were distributed using a set of weights due to differences in food supply from 1192 (EPIC) and 2006 (EPiGEICAM); first y of f/u excluded to minimize risk of reverse causality; - Funding: Alcala de Henares and Autonomous community of Madrid; International Agency for Research on Cancer; Department of Epidemiology and Biostatistics, School of Public Health, Imperial College London; Health Research Fund—Instituto de Salud Carlos III, the Regional Governments of Andalucía, Asturias, Basque Country, Murcia and Navarra, and the Catalan Institute of Oncology (Spain)
Chang, 2023 ^4^; United Kingdom; UK BIOBANK; Analytic N=197426; Participant characteristics:; - BMI, OW: 41%; Ob 21%; Normal, 37%;; - 4% CVD; 4% DM; 26% High-BP; Smokers: 57% never; 36% Family Hx of Cx; 37% HRT “ever” (♀); - 95% White, 0.5% Mixed; 1.4% South Asian; 1.2% Black; 1% Chinese or other; - Education: 43% university/college (13% A/AS; 25% O; 10% vocational; 8% not listed); Selection data: Excluded those with or who: were pregnant/unsure, implausible/extreme TEI; <1 24-hr recall; pre-existing Cx | DP Age(s): 58 years, mean (SD: 8) (40 to 69 at baseline); DP and DP Components: UPF, Nova Classification System Group 4 [Monteiro, 2019] (Table 1, Q4 > Q1 intakes): Higher intakes of Processed Meat; Total Fat; Total Carbohydrates; Total Sodium; Lower intakes of Vegetables; Fruit; Red Meat; Alcohol UPF, Nova 4 (Fig. 1 top sources): Carbonated drinks; Fruit-based drinks; Ready-to-eat/heat foods; Industrial-processed breads; Dairy-based drinks; Pastries, buns, cakes; Sausage and other reconstituted meat products; Other beverages; Industrial-processed desserts; Sauces and spreads; Biscuits; Breakfast cereals; Confectionary; Packaged salty snacks; Alcoholic drinks; Sweeteners; Meat alternatives; Lower in Tea, Coffee; Fruit, Vegetables; Fruit juice; Beer and Wine; Cheese; DP Method(s): Index/Score Analysis | Follow-up: 9.8 years, median; [underlined: Risk of Postmenopausal BCx]; Nova 4; per-10%, HR: 1.00 (0.95, 1.04); Q2, HR: 0.89 (0.77, 1.02); Q3, HR: 0.94 (0.81, 1.08); Q4, HR: 1.01 (0.87, 1.18); p-trend=0.7 | - Did not account for: Screening Diet assessment: 24-hr recalls, web-based ( 1 to 6); - Outcomes: Incident cases identified registry linkage; Cx defined by ICD codes; - n= 15921 Cx cases identified (BC: n=3030; CRC: n=1670, Color n=1091, rectum n=579); - Funding: Cancer Research UK; World Cancer Research Fund (WCRF) UK
Chebet, 2020 ^5^; United States; Women’s Health Initiative, WHI; Analytic N=9886; Participant characteristics:; - BMI, mean: 31.1; OW: ~60%, Ob: 24%; - Smokers: 50% never; - 100% Black; - HH Income: 86% ≤ $74,999/y; Education: 75% college (some or degree) or higher; - HH Income: 86% ≤ $74,999/y; Education: 75% college (some or degree) or higher; Selection data: Excluded those with or who had: severe clinical conditions (incl. Cx); predicted short survival, males, non-Black, unknown BMI, implausible TEI; incomplete or missing data (diet, PA, SEP, smoking, F/U) | DP Age(s): 50 to 59y, ~40%; 60 to 69y, ~43%; 70 to 79y, ~16%; DP and DP Components: Healthy Eating Index (HEI-2015) [Krebs-Smith 2018]HEI-2015: Positive: Total Vegetables; Greens and Beans; Total Fruit; Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; PUFA+MUFA/SFA. Negative: Refined Grains; Added Sugars; SFA; Sodium; DP Method(s): Index/Score Analysis | Follow-up: 13 years, mean; [underlined: Risk of BCx, all Postmenopausal]; EDIH & HEI-2015, HR: 0.97, 95% CI: 0.87, 1.09 | - Did not account for: Screening; - Diet assessment: FFQ (verified sub-set with RCT); - Outcomes: Incident cases identified by self-report, verified by physicians and/or medical records, NDI if LFU; Cx defined by ICD codes;; - BC cases identified: n=500; CRC cases identified: n=197); - Funding: NIH: NCI, NHLBI
Gardeazabal, 2020 ^8^; Spain; SUN; Analytic N=10713; Participant characteristics:; - BMI, mean: ~22.2; - <2% DM; Smokers: 48–53% never; ~33–38% current HRT; 78–95% premenopause; - Spanish; - Education, mean at university: ~5y; Selection data: Excluded those with or who: were male, pre-existing BC, invalid TEI; menopause < age 35y | DP Age(s):34.5y, mean (SD: 10.8); DP and DP Components: “Western” DP: high intakes of high-fat dairy products, processed meat, refined grains, sweets, caloric drinks, convenience food and sauces [e.g., crackers, snacks, egg derivatives; processed white/blue fish]; Low intakes of low-fat dairy products and whole grains; “Mediterranean” DP: high intakes of fish, vegetables, legumes [Peas, lentils, chickpeas, beans and broad beans], boiled potatoes, fruits, olives, and vegetable oil; Low intake of [veg./fruit] juices; DP Method(s): Factor/Cluster Analysis: PCA | Follow-up: 10.3 years, median; [underlined: Risk of Postmenopausal BCx]; “Western” DP; Q2, HR: 2.49 (0.86, 7.18); Q3, HR: 1.51 (0.47, 4.87); Q4, HR: 1.77 (0.57, 5.56); p-trend=0.548; “Mediterranean” DP; Q2, HR: 1.07 (0.32, 3.59); Q3, HR: 0.67 (0.18, 2.54); Q4, HR: 0.86 (0.21, 3.47); p-trend=0.686 | - Did not account for: Race/Ethnicity, Screening; - Diet assessment: FFQ; - Outcomes: Incident cases identified by self-report, verified by physicians and/or medical records as confirmed or probable; NDI if needed; Cx defined by ICD codes;; - BC cases identified: n=500; CRC cases identified: n=197; - Similar results were reported when examining only probable cases of BC (main analyses use confirmed cases); - Funding: Spanish Instituto de Salud Carlos III (ISCIII)/CIBEROBN (the Centro de Investigac on Biomedica en Red de Fisiopatologıa de la Obesidad y Nutricion), which are funded by FEDER/Spanish Government; Navarra Regional Govt.; University of Navarra
Jin, 2023 ^9^; United States; Women’s Health Initiative, Dietary Modification (WHI-DM) Trial; Analytic N=112468; Participant characteristics:; - BMI, mean: 26–30; 33–35% OW; 18-40% Ob across DP quintiles; - 100% postmenopausal; Smokers: 5-13% current; 12–14% use Aspirin/NSAIDs; - ~ 77–92% “White“, 4–16% “Black“, 2.5–8% “Hispanic/Latino“,1.3–5% “Asian/Pacific Islander“, 1–2% Other, < 1% “American Indian or Alaska Native“; - Education: ~28–51% ≥ 4y of college; ~46–62% high-school or lessEducation: ~28–51% ≥ 4y of college; ~46–62% high-school or less; Selection data: Excluded those with or who: were in the DM arm; existing Cx; implausible/missing/extreme TEI/BMI; incomplete or missing FFQ at baseline; 4y lag or lower GI Dz (e.g., Chron’s); missing outcome | DP Age(s):50 to 59y, ~40%; 60 to 69y, ~43%; 70 to 79y, ~16%; DP and DP Components: Empirical Dietary Indices for Hyperinsulinaemia (EDIH) [Tabung, 2016] Empirical Dietary Inflammatory Pattern, reverse-coded (rEDIP) [Tabung, 2016] Healthy Eating Index (HEI-2015) [Krebs-Smith 2018]EDIH: Positive: Red meat; Processed meat; Poultry; Tomatoes; French fries, Fish (non-dark); Low-fat dairy; Eggs; High-energy beverages (cola and other carbonated beverages with sugar, fruit drinks); Low-energy beverages; Margarine; Cream soups; Negative: Green leafy vegetables; Whole fruit; High-fat dairy products; Coffee; Wine rEDIP, Positive (Anti-Inflammatory): Vegetables (dark yellow: carrots, or squash), Vegetables (leafy green: cabbage, spinach, lettuce); Fruit juice (apple, cantaloupe, orange, or other fruit juice); Pizza; Snacks (cracker, potato chips); Tea; Coffee. Negative (Pro-Inflammatory): Vegtables, other: mixed, green pepper, cooked mushroom, eggplant, zucchini, or cucumber); Processed meat (sausage); Red meat (beef, or lamb); Organ meat (beef, calf, or chicken liver), Fish, canned tuna; Refined grains (white bread, biscuit, white rice, pasta, or vermicelli); High- and low-energy beverages (cola with sugar, carbonated beverages with sugar, fruit punch drinks); Tomatoes HEI-2015: Positive: Total Vegetables; Greens and Beans; Total Fruit; Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; PUFA+MUFA/SFA. Negative: Refined Grains; Added Sugars; SFA; Sodium; DP Method(s): Index/Score Analysis | Follow-up:17.8y, median; [underlined: Risk of BCx, all postmenopausal]; [underlined: Invasive BCx]; EDIH; Q2, HR: 1.08(0.98,1.19); Q3, HR: 1(0.91,1.11); Q4, HR: 1.04(0.94,1.15); Q5, HR: 1.14(1.02,1.26); p-trend=0.0458; per SD, HR: 1.03(0.99,1.06); p=0.1074; rEDIP; Q2, HR: 1.09(0.98,1.20); Q3, HR: 1.06(0.95,1.18); Q4, HR: 1.11(0.99,1.25); Q5, HR: 1.09(0.96,1.23); p-trend=0.1785; per SD, HR: 1.04(0.99,1.08); p=0.1053; HEI-2015; Q2, HR: 0.96(0.87,1.05); Q3, HR: 0.92(0.84,1.01); Q4, HR: 0.94(0.85,1.04); Q5, HR: 1.02(0.92,1.13); p-trend=0.8739; per SD, HR: 1(0.97,1.04); p=0.8875; [underlined: ER+ BCx]; EDIH; Q2, HR: 1.07(0.97,1.19); Q3, HR: 1.02(0.92,1.14); Q4, HR: 1.04(0.93,1.17); Q5, HR: 1.1(0.98,1.24); p-trend=0.1639; per SD, HR: 1.01(0.98,1.05); p=0.4995; rEDIP; Q2, HR: 1.08(0.97,1.21); Q3, HR: 1.08(0.96,1.21); Q4, HR: 1.11(0.98,1.26); Q5, HR: 1.04(0.90,1.19); p-trend=0.4851; per SD, HR: 1.02(0.97,1.06); p=0.5082; HEI-2015; Q2, HR: 0.96(0.86,1.06); Q3, HR: 0.95(0.85,1.06); Q4, HR: 0.98(0.88,1.09); Q5, HR: 1.06(0.95,1.19); p-trend=0.2687; per SD, HR: 1.02(0.98,1.06); p=0.3057; [underlined: ER− BCx]; EDIH; Q2, HR: 1.22(0.93,1.60); Q3, HR: 1.05(0.79,1.41); Q4, HR: 1.02(0.76,1.38); Q5, HR: 1.34(1.00,1.80); p-trend=0.1455; per SD, HR: 1.12(1.02,1.22); p=0.0198; rEDIP; Q2, HR: 0.98(0.74,1.31); Q3, HR: 1.02(0.75,1.40); Q4, HR: 1.24(0.90,1.71); Q5, HR: 1.2(0.85,1.71); p-trend=0.1575; per SD, HR: 1.12(0.99,1.26); p=0.0719; HEI-2015; Q2, HR: 0.86(0.67,1.12); Q3, HR: 0.82(0.63,1.07); Q4, HR: 0.79(0.60,1.03); Q5, HR: 0.84(0.64,1.11); p-trend=0.1468; per SD, HR: 0.95(0.87,1.04); p=0.298; [underlined: PR+ BC]; EDIH; Q2, HR: 1.1(0.98,1.23); Q3, HR: 1.06(0.94,1.20); Q4, HR: 1.05(0.93,1.19); Q5, HR: 1.13(1.00,1.28); p-trend=0.126; per SD, HR: 1.02(0.98,1.06); p=0.3071; EDIP; Q2, HR: 1.11(0.99,1.25); Q3, HR: 1.15(1.02,1.31); Q4, HR: 1.16(1.01,1.32); Q5, HR: 1.04(0.89,1.21); p-trend=0.4215; per SD, HR: 1.02(0.96,1.07); p=0.5488; HEI-2015; Q2, HR: 0.93(0.83,1.05); Q3, HR: 0.94(0.84,1.06); Q4, HR: 0.97(0.87,1.09); Q5, HR: 1.02(0.91,1.15); p-trend=0.6067; per SD, HR: 1.01(0.97,1.05); p=0.6053; [underlined: PR− BC]; EDIH; Q2, HR: 1.08(0.89,1.31); Q3, HR: 0.97(0.79,1.19); Q4, HR: 1.03(0.83,1.27); Q5, HR: 1.17(0.95,1.45); p-trend=0.2193; per SD, HR: 1.05(0.98,1.13); p=0.1383; EDIP; Q2, HR: 0.96(0.79,1.18); Q3, HR: 0.83(0.66,1.04); Q4, HR: 1.04(0.83,1.32); Q5, HR: 1.07(0.83,1.37); p-trend=0.5163; per SD, HR: 1.06(0.97,1.16); p=0.201; HEI-2015; Q2, HR: 0.96(0.79,1.16); Q3, HR: 0.91(0.74,1.10); Q4, HR: 0.87(0.72,1.07); Q5, HR: 0.98(0.80,1.20); p-trend=0.5911; per SD, HR: 0.99(0.93,1.06); p=0.7876; [underlined: HER2+ BC]; EDIH; Q2, HR: 0.99(0.73,1.35); Q3, HR: 1.02(0.74,1.40); Q4, HR: 1.01(0.73,1.40); Q5, HR: 1.21(0.87,1.68); p-trend=0.2444; per SD, HR: 1.08(0.97,1.19); p=0.1506; EDIP; Q2, HR: 1.25(0.91,1.72); Q3, HR: 1.2(0.85,1.70); Q4, HR: 1.19(0.82,1.73); Q5, HR: 1.26(0.85,1.88); p-trend=0.3513; per SD, HR: 1.08(0.95,1.24); p=0.2447; HEI-2015; Q2, HR: 0.85(0.63,1.14); Q3, HR: 0.85(0.63,1.15); Q4, HR: 0.92(0.68,1.24); Q5, HR: 0.91(0.67,1.24); p-trend=0.6721; per SD, HR: 0.98(0.88,1.08); p=0.6887; [underlined: HER2− BCx]; EDIH; Q2, HR: 1.09(0.98,1.21); Q3, HR: 1.02(0.91,1.14); Q4, HR: 1.05(0.94,1.18); Q5, HR: 1.1(0.97,1.24); p-trend=0.2238; per SD, HR: 1.02(0.98,1.06); p=0.3173; EDIP; Q2, HR: 1.09(0.97,1.22); Q3, HR: 1.05(0.93,1.19); Q4, HR: 1.11(0.98,1.27); Q5, HR: 1.05(0.91,1.22); p-trend=0.4033; per SD, HR: 1.02(0.98,1.08); p=0.3273; HEI-2015; Q2, HR: 0.96(0.86,1.06); Q3, HR: 0.95(0.86,1.06); Q4, HR: 0.94(0.84,1.05); Q5, HR: 1.04(0.93,1.17); p-trend=0.6159; per SD, HR: 1.01(0.97,1.05); p=0.6315; [underlined: ER− PR− HER 2+ BCx]; EDIH; Q2, HR: 0.92(0.52,1.65); Q3, HR: 1.02(0.57,1.84); Q4, HR: 1.03(0.56,1.88); Q5, HR: 0.92(0.49,1.75); p-trend=0.9036; per SD, HR: 1(0.82,1.22); p=0.9904; EDIP; Q2, HR: 1.89(1.01,3.53); Q3, HR: 1.37(0.67,2.80); Q4, HR: 1.73(0.82,3.64); Q5, HR: 1.79(0.80,3.97); p-trend=0.2604; per SD, HR: 1.06(0.82,1.38); p=0.6553; HEI-2015; Q2, HR: 0.72(0.41,1.25); Q3, HR: 0.74(0.43,1.29); Q4, HR: 0.75(0.43,1.32); Q5, HR: 0.74(0.41,1.32); p-trend=0.3243; per SD, HR: 0.92(0.76,1.12); p=0.4273; [underlined: luminal A (ER+ and/or PR+, HER2−) BCx]; EDIH; Q2, HR: 1.06(0.94,1.18); Q3, HR: 1.01(0.90,1.14); Q4, HR: 1.05(0.93,1.18); Q5, HR: 1.06(0.93,1.20); p-trend=0.4648; per SD, HR: 1(0.96,1.04); p=0.8666; EDIP; Q2, HR: 1.09(0.97,1.23); Q3, HR: 1.06(0.93,1.20); Q4, HR: 1.09(0.95,1.25); Q5, HR: 1.04(0.89,1.20); p-trend=0.6258; per SD, HR: 1.01(0.96,1.07); p=0.5888; HEI-2015; Q2, HR: 0.96(0.86,1.08); Q3, HR: 0.96(0.86,1.08); Q4, HR: 0.96(0.85,1.08); Q5, HR: 1.05(0.94,1.19); p-trend=0.4815; per SD, HR: 1.01(0.97,1.05); p=0.57; [underlined: Luminal B (ER+ and/or PR+, HER2+) BC]; EDIH; Q2, HR: 1.04(0.72,1.51); Q3, HR: 1.05(0.72,1.53); Q4, HR: 1.04(0.70,1.52); Q5, HR: 1.35(0.92,1.98); p-trend=0.1418; per SD, HR: 1.11(0.99,1.25); p=0.0827; EDIP; Q2, HR: 1.06(0.73,1.55); Q3, HR: 1.14(0.77,1.69); Q4, HR: 1.01(0.65,1.56); Q5, HR: 1.08(0.68,1.71); p-trend=0.8397; per SD, HR: 1.08(0.92,1.27); p=0.3545; HEI-2015; Q2, HR: 0.89(0.62,1.27); Q3, HR: 0.91(0.64,1.31); Q4, HR: 1.03(0.72,1.47); Q5, HR: 1.01(0.70,1.46); p-trend=0.7698; per SD, HR: 1.02(0.90,1.15); p=0.7911; [underlined: Triple Negative (TN) BCx]; EDIH; Q2, HR: 1.43(1.01,2.02); Q3, HR: 1.06(0.72,1.54); Q4, HR: 1.1(0.74,1.62); Q5, HR: 1.52(1.04,2.21); p-trend=0.1159; per SD, HR: 1.16(1.04,1.31); p=0.0086; EDIP; Q2, HR: 0.97(0.67,1.40); Q3, HR: 0.98(0.66,1.45); Q4, HR: 1.24(0.83,1.86); Q5, HR: 1.14(0.73,1.78); p-trend=0.3461; per SD, HR: 1.11(0.95,1.30); p=0.1842; HEI-2015; Q2, HR: 0.91(0.66,1.27); Q3, HR: 0.89(0.64,1.24); Q4, HR: 0.77(0.54,1.09); Q5, HR: 0.92(0.65,1.30); p-trend=0.4195; per SD, HR: 0.98(0.87,1.09); p=0.6646; [underlined: Localized BCx]; EDIH; Q2, HR: 1.08(0.96,1.21); Q3, HR: 1.02(0.91,1.16); Q4, HR: 1.05(0.93,1.18); Q5, HR: 1.14(1.00,1.29); p-trend=0.0845; per SD, HR: 1.04(1.00,1.08); p=0.034; EDIP; Q2, HR: 1.13(1.00,1.27); Q3, HR: 1.07(0.94,1.22); Q4, HR: 1.15(1.01,1.32); Q5, HR: 1.11(0.96,1.29); p-trend=0.1732; per SD, HR: 1.04(0.99,1.10); p=0.125; HEI-2015; Q2, HR: 0.98(0.87,1.09); Q3, HR: 0.96(0.86,1.08); Q4, HR: 0.95(0.85,1.07); Q5, HR: 1.05(0.94,1.19); p-trend=0.5398; per SD, HR: 1.01(0.97,1.05); p=0.5121; Regional/distant BC; EDIH; Q2, HR: 1.09(0.90,1.31); Q3, HR: 0.97(0.79,1.19); Q4, HR: 1.06(0.86,1.30); Q5, HR: 1.13(0.92,1.39); p-trend=0.329; per SD, HR: 0.98(0.92,1.05); p=0.6611; EDIP; Q2, HR: 0.99(0.81,1.21); Q3, HR: 1.06(0.85,1.31); Q4, HR: 1.08(0.86,1.36); Q5, HR: 1.01(0.79,1.30); p-trend=0.7094; per SD, HR: 1.01(0.93,1.11); p=0.7472; HEI-2015; Q2, HR: 0.94(0.78,1.13); Q3, HR: 0.87(0.72,1.05); Q4, HR: 0.95(0.78,1.16); Q5, HR: 1.01(0.83,1.23); p-trend=0.9431; per SD, HR: 1(0.94,1.06); p=0.9592 | - Did not account for: Screening (BC only); - Diet assessment: FFQ (verified sub-set with RCT); - Outcomes: Incident cases identified by self-report, verified by physicians and/or medical records, NDI if LFU; Cx defined by ICD codes; Sub-types of BC defined by SEER; - Total Cx cases identified: n=18768; - Results are in Table S5 (MV models adj. BMI); Results between each DP & invasive ductal or lobular carcinoma also reported; - Funding: NCI; ACS; NIH (NHLBI)
Maimaitiyiming, 2023 ^10^; United Kingdom; UK BIOBANK; Analytic N=114289; Participant characteristics:; - BMI, mean: 25–28.5; - 17–27% HTN, 2–7% DM; 2–6% CVD; Smokers: 49–62% never; ~33–36% current HRT; - ~100% White; - Townsend: ~−1.48 to −1.77;; - Education: 84–94% higher/degree; Selection data: Excluded those with or who: <1 diet assessment; Dx of Cx; implausible/extreme TEI; withdrew | DP Age(s):~56 years, mean across DP quartiles (40 to 69 at baseline); DP and DP Components: “Obesity-related” DP characterized by: Higher intake of beer and cider, processed meat, high-sugar beverages, red meat, and artifcial sweetener (Other positive loadings, 0.40 to 0.10: Crisps, chips, savory snacks; instant coffee; spirits/liquors; ice cream; frozen vegetable; egg and egg dishes; added sugars; breaded meat/fish; buns, cakes etc.; white bread; poultry; other breakfast cereals; PUFA margarine; boiled/baked potato; liver; legumes); Lower intake of fresh vegetables, olive oil, tea, and high fber breakfast cereals (Other negative loadings, −0.20 to 0.0: water; other milk; nuts and seeds; fruits; cereals; meat alternatives; oily fish; whole grain cereals; low-fat butter; other coffee; other fish; low-fat cheese; wine); DP Method(s): RRR | Follow-up: 9.4 years, median; [underlined: Risk of Postmenopausal BCx]; “Obesity-related” DP; linear, HR: 0.99 (0.95,1.04); Q2, HR: 1.11 (1.02,1.20); Q3, HR: 0.92 (0.83,1.01); Q4, HR: 1.05 (0.93,1.17); p=0.009; Complete-case, HR: 1.00 (0.95, 1.05); p=0.993 | - Did not account for: Screening; - Diet assessment: 24-hr recalls, web-based; - Outcomes: Methods NR; Cx defined by ICD; - CRCx, n=1218; Premenopausal BCx, n=809; postmenopausal BCx, n=1190; - Results also reported excluding first 2y F/U and stratified by sex; age; smoking; physical acivity; DM; HTN; CVD; - Funding: None reported for study
Männistö, 2021 ^11^; Finland; Prospective Meta-Cohort Study of Cancer Burden in Finland (METCA project); Analytic N=6374; Participant characteristics:; - BMI, median: 27; - Smokers: 8–21% current; - 0–69% ever HRT; - Finnish; Selection data: Excluded those with or who had: “unacceptable” dietary info, Dx of Cx, <50y | DP Age(s):57 to 63y, mean across 5 cohorts (≥50y at baseline); DP and DP Components: modfied Nordic Diet score (mNDI) [modified Baltic Sea Diet score, Kanerva, 2014]; removed total fat intake; replaced fiber with whole grains (mBSD), Positive: Vegetables (not potatoes); Fruit; Fish; Low-fat milk; PUFA:SFA/Trans FA; Whole-grain products; Negative: Red and Processed meat products; Neutral: Alcohol; Alternate Med Diet Score (AMED) [Fung 2005]; reported as “modified” MDS but reflects aMED, Positive: Vegetables (not potatoes); Legumes; Fruit; Nuts; Whole Grains; Fish; MUFA/SFA. Negative: Red Meat. Neutral: Alcohol; mAHEI: Positive: Vegetables (not potatoes, French fries); Fruit; Nuts and Soy Protein; Whole Grains; White: Red Meat Ratio; PUFA:SFA; Multi-Vitamin Use. Negative: Trans-UFA. Neutral: Alcohol; DP Method(s): Index/Score Analysis | Follow-up: 10 years, mean from 5 cohorts combined (~25; 15; 12; 10, and 5 year follow-ups); [underlined: Risk of Postmenopausal BCx]; mNDI; Q2, HR: 1.19 (0.78–1.82); Q3, HR: 1.17 (0.76–1.79); Q4, HR: 1.18 (0.77–1.80); Q5, HR: 0.83 (0.52–1.33); p-trend=0.50; excluding cohort as confounder=0.31; aMED; Q2, HR: 0.91 (0.61–1.36); Q3, HR: 0.63 (0.40–0.99); Q4, HR: 0.69 (0.45–1.06); Q5, HR: 0.87 (0.56–1.34); p-trend=0.27; excluding cohort as confounder=0.23; mAHEI; Q2, HR: 1.17 (0.76–1.78); Q3, HR: 1.21 (0.79–1.85); Q4, HR: 0.99 (0.63–1.55); Q5, HR: 1.03 (0.66–1.61); p-trend=0.8; p-excluding cohort as confounder=0.21 | - Did not account for: Race/Ethnicity (all Finnish), Screening; - Diet assessment: Diet Hx or FFQ; - Outcomes: Incident cases identified by cancer registry linkage; all presumed postmenopausal; - BC cases identified: n=274; - When excluding alcohol as a moderate component of the DP, the strength of the inverse association was attenuated between each index & BC risk; - Funding: None reported for study
Neuhouser, 2022 ^12^; United States; Women Health Initiative (WHI); Analytic N=100374; Participant characteristics:; - BMI, mean: 27.6; - Smokers: 51% never; 40% current HRT; - 84.5% White, non-Hispanic; 7.7% Black, non-Hispanic; 3.3% Hispanic/Latina; 2.8% Asian/Pacific Islander; - Education: 42.4% ≥ college degreeEducation: 42.4% ≥ college degree; Selection data:Excluded those with Hx of CVD | DP Age(s): 63.6y, mean (50 to 79 y), postmenopause; DP and DP Components: HEI-2010HEI-2010, Positive: Total Vegetables; Greens and Beans; Total Fruit; Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; Fatty Acids. Negative: Refined Grains; Added Sugars in “Empty Calories“; Solid Fats in “Empty Calories“; Sodium; DP Method(s): Index/Score | Follow-up: 22–26y ~; [underlined: Risk of BCx, all postmenopausal]; HEI-2010 (Uncal per 20%), HR: 0.98, 95% CI: 0.95, 1.01; HEI-2010 (Cal per 20%), HR: 0.97, 95% CI: 0.87, 1.08 | - Did not account for: Screening; - Diet assessment: FFQ (verified sub-set with RCT); - Outcomes: Incident cases identified via self-report then confirmed via medical records/pathology with physician review;; - cases identified: n=2364 (BCx); n=2315 (CRCx); - Calibration of FFQ HEI-2010 scores attempted to improve properties of self-reported diet and minimize error; Predominantly participants are NHW, so the findings may not be generalizable.; - Funding: NIH/NHLBI
Peila, 2022 ^13^; United Kingdom; UK BIOBANK; Analytic N=105680; Participant characteristics:; - BMI, mean: 22.4–22.8 (all 18.5 - <25.0); - <2% DM;; - Smokers: <11% never; current HRT varied:; - ~3% premenopausal; - ~11–17% postmenopausal; - 93–97% White; - Townsend: ~−1.4 to −1.9; Selection data: Excluded those with or who: missing diet assessment; Dx of Cx; withdrew/LFU | DP Age(s): ~60 years (40 to 69 at baseline); DP and DP Components: Healthy lifestyle index (HLI)-diet only [Author, 2020 adapted WCRF/AICR score of Romaguera 2012], diet only, Positive: Vegetables, Fruit; Whole grains. Negative: Red Meat; Processed Meat; Alcohol; DP Method(s): Index/Score | Follow-up: 7 years, mean (SD: 1.1); [underlined: Risk of Postmenopausal BCx]; HLI-diet only; 2, HR: 0.90 (0.78,1.05); 3, HR: 0.91 (0.76,1.08); p-trend=0.220 | - Did not account for: Race/Ethnicity (93–97% White), Screening, Postmenopausal hormone therapy; - Diet assessment: 24-hr recalls, web-based; - Outcomes: Incident cases identified via national health services/information center; CX defined by ICD codes; - Cases of BCx identified: n=1796; Postmenopausal, n=1,236; Premenopausal, n=560); - Funding: Advertisement “The costs of publication of this article were defrayed in part by the payment of page charges. This article must therefore be hereby marked advertisement in accordance with 18 U.S.C. Section 1734 solely to indicate this fact“
Romanos-Nanclares, 2022 ^15^; United States; NHS; NHS II; Analytic N=0; Participant characteristics:; - BMI, mean: ~ 23 to 26.5, (range NHS & NHSII); - WC, cm, mean: ~75.2 to 82.7; - Hx of DM: ~0.6 to 6%; - Family Hx of BC: ~8% NHS, ~6% NHSII; - Biopsy-confirmed benign breast disease: 25–28% NHS; 9–10% NHSII; - Oral contraceptive use: ~49.5% NHS, ~84–85% NHSII; - Postmenopausal: ~48% NHS, ~3% NHSII; - Postmenopausal HRT, never: ~52% NHS; 7% NHSII; - 95–97% White; - SEP NR, 100% health professionals Selection data: Excluded those with: missing values for EDIH; Cx (except nonmelanoma skin Cx); implausible baseline TEI (< 600 or > 3500 kcal/d) | DP Age(s):36 to 52 years [49.2 to 52.3 (range: 38–63), NHS I; 36 to 37.5 years (range: 27–44), NHS II]; DP and DP Components: Empirical dietary index for hyperinsulinemia (EDIH) [Tabung, 2016], Negative: Green leafy vegetables; Whole fruit; High-fat dairy products; Coffee; Wine; Positive: Red meat; Processed meat; Poultry; Tomatoes; French fries, Fish (other than dark-meat fish); Low-fat dairy; Eggs; High-energy beverages (cola and other carbonated beverages with sugar, fruit drinks); Low-energy beverages; Margarine; Cream soups;; DP Method(s): Index/Score Analysis | Follow-up: 26 to 32 years; [underlined: Risk of Postmenopausal BCx]; EDIH & Invasive,; Q2 HR: 1.03 (0.96, 1.10); Q3 HR: 1.03 (0.96, 1.11); Q4 HR: 1.12 (1.04, 1.21); Q5 HR: 1.19 (1.10, 1.29); P-trend <0.001; EDIH & ER-negative,; Q2 HR: 1.10 (0.90, 1.33); Q3 HR: 1.09 (0.89, 1.33); Q4 HR: 1.22 (0.99, 1.50); Q5 HR: 1.29 (1.03, 1.62); P-trend =0.02 | - Did not account for: Smoking, Screening; - Diet assessment: FFQ every 4 y; - Outcomes: Incident cases identified via medical record review and self-reported cases confirmed by the nurse; luminal A tumors: ER-positive and/or PR− positive, HER2-negative, and Ki-67-negative (or histologic grade 1 or 2); luminal B tumors: either ER-positive and/or PR-positive and HER2-positive or 2) ER-positive and/or PR-positive, HER2-negative, and Ki-67-positive (or histologic grade 3); HER2-enriched tumors: ER-negative, PR-negative, and HER2-positive; Basal-like tumors: ER− negative, PR-negative, HER2-negative, and CK 5/6-positive and/or EGFR-positive; ER status determined from TMA slides, and secondarily from pathology; - Funding: NIH, Breast Cancer Research Foundation, Ramon Areces Foundation and Susan G Komen Foundation
Romanos-Nanclares, 2020 ^16^; Spain; SUN; Analytic N=10812; Participant characteristics:; - BMI, kg/m2: ~22.2; - PA, METs-h/week: 19.9–20.6; - Diabetes, %: 0.94 –1.34; - Smoking, Never: 48.8–53.9%; - Family history of breast cancer: ~11%; - Postmenopausal, %: 9.4–14.0; - Postmenopausal ≥ 50 y, %: 47; - Spanish; - Education: ~4.8 y university Selection data: Excluded those who were recruited after 2015 October, LFU, prevalent BC, TEI outside predefined limits, or reported menopause at age < 35 y | DP Age(s):~35 years, mean; DP and DP Components: Provegetarian Food Pattern [Martinez-Gonzalez 2014], Positive: Vegetables; Potatoes; Legumes; Fruits; Nuts; Cereals; Vegetable fat; Pastries; Sugar-sweetened beverages; Coffee. Negative: Fish and Other Seafood; Meats and Meat Products; Eggs; Dairy Products; Animal Fats for cooking or as a spread Healthy PVG, fitted from hPDI [Satija, 2016], Positive: Vegetables; Boiled or Baked Potatoes; Legumes; Fruits; Nuts; Whole Grains; Vegetable oil and Coffee; Negative: Pastries; Refined Grains; French Fries; Sugar-sweetened beverages; Fish and Other Seafood; Meats and Meat Products; Eggs; Dairy; Products; Animal Fats for cooking or as a spread; Other Vegetable Fats; Unhealthy PVG, fitted from uPDI [Satija, 2016], Negative: Vegetables; Boiled or Baked Potatoes; Legumes; Fruits; Nuts; Whole Grains; Vegetable oil and Coffee; Negative: Pastries; Refined Grains; French Fries; Sugar-sweetened beverages; Fish and Other Seafood; Meats and Meat Products; Eggs; Dairy; Products; Animal Fats for cooking or as a spread; Other Vegetable Fats; DP Method(s): Index/Score Analysis | Follow-up: 11.5 years, median; [underlined: Risk of Postmenopausal BCx]; PVG; T2 HR 0.96 (0.41, 2.24); T3 HR 1.41 (0.61, 3.24); P for trend=0.431; hPVG; T2, HR 1.17 (0.54, 2.54); T3, HR 0.71 (0.28, 1.84); P for trend=0.525; uPVG; T2 HR 2.57 (1.03, 6.43); T3 HR 2.12 (0.76, 5.68); P for trend=0.177 | - Did not account for: Race/Ethnicity (Spanish), Screening; - Diet assessment: FFQ; - Outcomes: Incident cases identified via self-reported Dx and confirmed by physician medical record review; - Additional analyses with probable incident BC cases but results hardly changed; - Limited generalizibility; self-reported case; one-time diet measurement; - Funding: the Spanish Government-Instituto de Salud Carlos III, the European Regional Development Fund, and the University of Navarra
Romanos-Nanclares, 2021 ^17^; United States; NHS; NHSII; Analytic N=0; Participant characteristics:; - BMI, kg/m2: ~25.0 NHS; 23.7 to 25.2 NHSII; - Hx of T2D: 2–4% NHS; ~1% NHSII; - Family Hx BC: 8% NHS; 6% NHSII; - Personal Hx benign breast disease: ~30% NHS; ~10% NHSII; - Postmenopausal: ~48.5% NHS; 3.2% NHSII; - African heritage: ~1.1–1.5% in NHS; 1.2 –2.0% in NHSII; - SEP NR; 100% health professionals; Selection data: Excluded women who died prior to baseline, had prevalent cancer, had missing dietary information, or reported implausible TEI | DP Age(s): 50y, ~ mean NHS; 37y, ~ mean NHS II; DP and DP Components:; modified Plant-Based Diet Index (mPDI), healthful/unhealthful PDI (mhPDI/muPDI) [Kim 2022 modified Satija, 2016 - removed vegetable oils (margarine) and alcohol from score]; mPDI: Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Tea/coffee; Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Negative: Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; mhPDI: Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Tea/coffee; Negative: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; muPDI: Negative: Whole grains; Fruits; Vegetables; Nuts; Legumes; Tea/coffee; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; Positive: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; DP Method(s): Index/Score Analysis | Follow-up: 32 years NHS; 26 years NHSII; [underlined: Risk of Postmenopausal BCx]; PDI & ER−, per 10 units, HR 0.90 (0.80, 1.01); hPDI & ER−, per 10 units, HR 0.86 (0.78, 0.95); uPDI & ER−, per 10 units, HR 1.10 (1.00, 1.21) | - Did not account for: Smoking, Screening; - Diet assessment: FFQ at baseline (collected every 4 y); - Outcomes: Incident cases identified via self-report and confirmed via medical record review or nurse; subtypes based on gene expression profiles; - Cohort-specific analyses showed similar results as overall; Results slightly attenuated adjusting weight change since age 18 for PDI; adjusting weight change, total carotenoid intake for hPDI; adjusting dietary fiber did not change the results; hPDI was inversely associated with both premenopausal and postmenopausal BCx; Analyses showed inverse relationship between PDI, hPDI & Basal-like BCx; Null association between uPDI & Basal-like; No effect modification by menopausal status, PA, or current BMI for diet and ER− BCx.Limited power for ER− negative BCx.; - Funding: NIH, the Breast Cancer Research Foundation; Spanish Association Against Cancer Scientific Foundation
Shah, 2023_Long-term ^18^; France; E3N; Analytic N=65574; Participant characteristics:; - BMI, kg/m2, mean: 22.92; - Smokers, current ~14%; - Hx of benign breast disease: 29%; - Family Hx BC: 7.4%; - NR (French); - Education: Undergraduate or less: 11%; Graduate: 53%; Postgraduate: 36%Education: Undergraduate or less: 11%; Graduate: 53%; Postgraduate: 36%; Selection data:Excluded those with undefined menopausal status, who had never menstruated, prevalent cancer cases, those with incomplete or absent follow-up information; those with extreme energy intake values, those with missing BC receptor status data, and those who had not attained menopause at the end of the follow-up | DP Age(s):5 2.9y, mean (range: 40–65y); DP and DP Components: Plant-Based Diet Index (PDI) healthful/unhealthful PDI (hPDI/uPDI) [Satija, 2016]PDI: Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Negative: Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; hPDI: Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Negative: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; uPDI: Negative: Whole grains; Fruits; Vegetables; Nuts; Legumes; Vegetable oils; Tea/coffee; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; Positive: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; DP Method(s): Index/Score Analysis | Follow-up: 21 years; [underlined: Risk of BCx, all postmenopausal]; Cumulative PDI & overall BC (Sensitivity analysis); Q2, HR 0.83, 95% CI: 0.75, 0.92; Q4, HR 0.84, 95% CI: 0.76, 0.93; Q5, HR 0.94, 95% CI: 0.85, 1.04; NS/Null: baseline overall PDI & BC risk; Time-dependent PDI & overall BC; Per 1-SD increase, HR 0.977, 95%; CI: 0.969, 0.985; Q5 vs. Q1, HR 0.94, 95% CI: 0.91, 0.96; hPDI & overall BC; Q2, HR 0.93, 95% CI: 0.85, 1.03; Q3, HR 0.79, 95% CI: 0.71, 0.87; Q4, HR 0.78, 95% CI: 0.70, 0.86; Q5, HR 0.86, 95% CI: 0.77, 0.95; P for trend<0.01; uPDI & overall BC; Per-SD increase: HR 1.04, 95% CI: 1.01, 1.08; Q2, HR 0.98, 95% CI: 0.89, 1.09; Q3, HR 0.99, 95% CI: 0.89, 1.10; Q4, HR 1.02, 95% CI: 0.92, 1.13; Q5, HR 1.20, 95% CI: 1.08, 1.33; P for trend<0.01; hPDI & ER+; Q2, HR 0.99, 95% CI: 0.89, 1.10; Q3, HR 0.79, 95% CI: 0.71, 0.89; Q4, HR 0.76, 95% CI: 0.68, 0.85; Q5, HR 0.85, 95% CI: 0.76, 0.95; P for trend<0.01; uPDI & ER+; Per-SD increase: HR 1.05, 95% CI: 1.01, 1.08; Q2, HR 0.98, 95% CI: 0.87, 1.09; Q3, HR 0.99, 95% CI: 0.88, 1.11; Q4, HR 1.07, 95% CI: 0.96, 1.19; Q5, HR 1.20, 95% CI: 1.07, 1.35; P for trend<0.01; hPDI & ER−; Q2, HR 0.68, 95% CI: 0.53, 0.86; Q3, HR 0.75, 95% CI: 0.59, 0.95; Q4, HR 0.85, 95% CI: 0.67, 1.08; Q5, HR 0.88, 95% CI: 0.69, 1.12; P for trend=0.88; uPDI & ER−; Per-SD increase: HR 1.03, 95% CI: 0.95, 1.12; Q2, HR 1.03, 95% CI: 0.81, 1.30; Q3, HR 0.98, 95% CI: 0.76, 1.26; Q4, HR 0.80, 95% CI: 0.62, 1.03; Q5, HR 1.20, 95% CI: 0.94, 1.53; P for trend=0.45; hPDI & PR+; Q2, HR 0.94, 95% CI: 0.84, 1.86; Q3, HR 0.78, 95% CI: 0.69, 0.89; Q4, HR 0.75, 95% CI: 0.66, 0.85; Q5, HR 0.87, 95% CI: 0.76, 0.99; P for trend<0.01; uPDI & PR+; Per-SD increase: HR 1.04, 95% CI: 1.00, 1.09; Q2, HR 0.96, 95% CI: 0.85, 1.09; Q3, HR 1.01, 95% CI: 0.89, 1.15; Q4, HR 1.03, 95% CI: 0.91, 1.17; Q5, HR 1.18, 95% CI: 1.03, 1.34; P for trend=0.02; hPDI & PR−; Q2, HR 0.92, 95% CI: 0.78, 1.08; Q3, HR 0.79, 95% CI: 0.67, 0.93; Q4, HR 0.83, 95% CI: 0.70, 0.98; Q5, HR 0.84, 95% CI: 0.70, 1.00; P for trend=0.02; uPDI & PR−; Per-SD increase: HR 1.05, 95% CI: 0.99, 1.11; Q2, HR 1.02, 95% CI: 0.87, 1.21; Q3, HR 0.96, 95% CI: 0.80, 1.14; Q4, HR 0.99, 95% CI: 0.84, 1.18; Q5, HR 1.24, 95% CI: 1.05, 1.47; P for trend=0.02; hPDI & ER+/PR+; Q2, HR 0.96, 95% CI: 0.85, 1.09; Q3, HR 0.80, 95% CI: 0.70, 0.90; Q4, HR 0.75, 95% CI: 0.66, 0.86; Q5, HR 0.86, 95% CI: 0.75, 0.99; P for trend<0.01; uPDI & ER+/PR+; Per-SD increase: HR 1.04, 95% CI: 1.00, 1.09; Q2, HR 0.97, 95% CI: 0.85, 1.10; Q3, HR 1.01, 95% CI: 0.88, 1.15; Q4, HR 1.05, 95% CI: 0.92, 1.19; Q5, HR 1.17, 95% CI: 1.02, 1.34; P for trend=0.02; hPDI & ER−/PR−; Q2, HR 0.71, 95% CI: 0.55, 0.93; Q3, HR 0.79, 95% CI: 0.61, 1.02; Q4, HR 0.89, 95% CI: 0.69, 1.15; Q5, HR 0.87, 95% CI: 0.67, 1.14; P for trend=0.81; uPDI & ER−/PR−; Per-SD increase: HR 1.04, 95% CI: 0.95, 1.13; Q2, HR 1.06, 95% CI: 0.82, 1.36; Q3, HR 0.97, 95% CI: 0.74, 1.26; Q4, HR 0.82, 95% CI: 0.62, 1.08; Q5, HR 1.19, 95% CI: 0.91, 1.55; P for trend=0.57; Baseline hPDI & overall BC; Per 1-SD increase, HR 0.97, 95% CI: 0.93, 1.00; Q5 vs Q1, HR 0.92, 95% CI: 0.83, 1.02, P for trend=0.06; Baseline uPDI & overall BC; Per 1-SD increase, HR 1.04, 95% CI: 1.01, 1.08; Q5 vs. Q1, HR 1.13, 95% CI: 1.02, 1.26, P for trend=0.02; Time-dependent hPDI & overall BC; Per 1-SD increase, HR 0.991, 95% CI: 0.983, 0.999; Q5 vs. Q1, HR 0.97, 95% CI: 0.94, 1.00; Time-dependent uPDI & overall BC; Per 1-SD increase, HR 0.997, 95% CI: 0.988, 1.005; Q5 vs. Q1, HR 0.99, 95% CI: 0.96, 1.01; Summary: Inverse: PDI (Q2, Q4; time-dependent per SD, Q5 v. Q1) & BC; NS/Null: baseline PDI & BC Inverse: hPDI & BC, ER+, ER−(Q2, Q3 vs. Q1), PR+, PR−, ER+/PR+; NS/Inverse: hPDI & ER−, ER−/PR−, ER−/PR−; Positive: uPDI (Q5, per SD) & BC; uPDI & ER+, PR+, PR−, ER+/P | - Did not account for: Race/Ethnicity, Screening; - Diet assessment: FFQ; - Outcomes: Incident cases identified through questionnaires inquiring about cancer occurrence, contact details of physicians, and from insurance and death certificates; hormone receptors and histology subtypes from clinical and pathology reports; - there is no interaction between cumulative average hPDI, uPDI and BMI, MHT use or physical activity in relation to BC (Supplemental table 8–10); analysis was also conducted on Ductal, Lobular and other histology type of BC (Supplemental table 7);; - Limited; - Funding: MGEN, Institut Gustave Roussy and the “Ligue; - contre le Cancer”; National Research Agency, “Investissement d’avenir“; “Minist ere de l’enseignement sup erieur de la recherche et de; - l’innovation“
Shah, 2023_Palaeolithic ^19^; France; E3N; Analytic N=65574; Participant characteristics:; - BMI, kg/m2, mean: 22.92; - Smokers, current ~14%; - Past history of benign breast disease: 29.05%; - Family history of breast cancer: 7.38%; - NR (French); - Education: Undergraduate or less: 11%; Graduate: 53%; Postgraduate: 36%Education: Undergraduate or less: 11%; Graduate: 53%; Postgraduate: 36%; Selection data: Excluded those with undefined menopausal status, those who had never menstruated, prevalent cancer cases, those who had never menstruated, prevalent cancer cases, with incomplete or absent follow-up information, those with extreme energy intake values, with missing BC receptor status, and those who had not attained menopause at the end of follow-up | DP Age(s):52.8y, mean (range: 40–65y); DP and DP Components: Paleolithic Score [Whalen 2014]Paleo, Positive: Vegetables; Fruit and Vegetable Diversity; Fruit; Nuts; Fish; Lean Meat; Calcium (from non-dairy foods). Negative: Grains and Starches; Baked Goods; Red and Processed Meat; Dairy Foods; Alcohol; Sodium; DP Method(s): Index/Score Analysis | Follow-up:20 y, mean; [underlined: Risk of BCx, all postmenopausal]; Paleolithic diet score (Paleo) & BCx; Per-SD increase, HR 0.92, 95% CI: 0.89, 0.95; Q2 HR 1.02, 95% CI: 0.93, 1.12; Q3 HR 0.75, 95% CI: 0.68, 0.83; Q4 HR 0.89, 95% CI: 0.81, 0.99; Q5 HR 0.83, 95% CI: 0.75, 0.92; P for trend<0.01; Paleo & ER+; Per-SD increase, HR 0.91, 95% CI: 0.88, 0.95; Q2 HR 1.05, 95% CI: 0.94, 1.16; Q3 HR 0.77, 95% CI: 0.69, 0.86; Q4 HR 0.89, 95% CI: 0.80, 0.99; Q5 HR 0.82, 95% CI: 0.73, 0.91; P for trend<0.01; Paleo & ER−; Per-SD increase, HR 0.96, 95% CI: 0.89, 1.04; Q2 HR 0.89, 95% CI: 0.70, 1.12; Q3 HR 0.68, 95% CI: 0.53, 0.86; Q4 HR 0.93, 95% CI: 0.74, 1.16; Q5 HR 0.90, 95% CI: 0.71, 1.14; P for trend=0.47; Paleo & PR+; Per-SD increase, HR 0.92, 95% CI: 0.88, 0.96; Q2 HR 0.98, 95% CI: 0.87, 1.11; Q3 HR 0.76, 95% CI: 0.67, 0.86; Q4 HR 0.88, 95% CI: 0.78, 1.00; Q5 HR 0.84, 95% CI: 0.74, 0.95; P for trend<0.01; Paleo & PR−; Per-SD increase, HR 0.92, 95% CI: 0.87, 0.97; Q2 HR 1.08, 95% CI: 0.93, 1.26; Q3 HR 0.73, 95% CI: 0.62, 0.86; Q4 HR 0.92, 95% CI: 0.78, 1.08; Q5 HR 0.82, 95% CI: 0.69, 0.97; P for trend<0.01; Paleo & ER+/PR+; Per-SD increase, HR 0.92, 95% CI: 0.88, 0.96; Q2 HR 0.99, 95% CI: 0.88, 1.12; Q3 HR 0.78, 95% CI: 0.69, 0.88; Q4 HR 0.87, 95% CI: 0.78, 0.99; Q5 HR 0.83, 95% CI: 0.73, 0.94; P for trend<0.01; Paleo & ER−/PR−; Per-SD increase, HR 0.95, 95% CI: 0.87, 1.03; Q2 HR 0.92, 95% CI: 0.72, 1.18; Q3 HR 0.72, 95% CI: 0.56, 0.93; Q4 HR 0.90, 95% CI: 0.70, 1.16; Q5 HR 0.87, 95% CI: 0.68, 1.12; P for trend=0.29; Paleo at baseline & BCx; Per-SD increase, HR 0.94, 95% CI: 0.91, 0.97; Q2, HR 1.02, 95% CI: 0.93, 1.13; Q3, HR 0.89, 95% CI: 0.80, 1.00; Q4, HR 0.93, 95% CI: 0.84, 1.02; Q5, HR 0.86, 95% CI: 0.78, 0.96; P for trend<0.01; Paleo, Time-dependent & BCx; Per-SD increase, HR 0.986, 95% CI: 0.978, 0.994; Q2, HR 1.00, 95% CI: 0.97, 1.02; Q3, HR 0.96, 95% CI: 0.94, 0.99; Q4, HR 0.96, 95% CI: 0.93, 0.98; Q5, HR 0.97, 95% CI: 0.94, 0.99; Summary: Inverse: Paleolithic diet score & BC, ER+, PR+, PR−, ER+/PR−; NS/Inverse: ER−, ER−/PR− | - Did not account for: Race/Ethnicity, Screening; - Diet assessment: FFQ; - Outcomes: Incident cases identified through questionnaires inquiring about cancer occurrence, contact details of physicians, and from insurance and death certificates; hormone receptors and histology subtypes from clinical and pathology reports; - Additional analyses on ductal, lobular, other histology type of cancer (inverse association, table 4); no interaction with BMI, ever use of MHT (Table 5–6); additional sensitivity analyses with covariates with missing imputed with MI; with data excluding; - Funding: MGEN, Institut Gustave Roussy and the “Ligue contre le Cancer”; National Research Agency, “Investissement d’avenir“; “Ministere de l’enseignement superieur de la recherche et de l’innovation“; l’Ecole Doctorale de Santé Publique, Ministère de l’enseignement supérieur, de la recherche et de l’innovation
Thompson, 2023 ^22^; United Kingdom; UK BIOBANK; Analytic N=126394; Participant characteristics:; - BMI, Overweight: 42%; Obesity 21%; - Smokers: 53–60% never; - 91% “White“, 0.4% “Black“, 4.6% “Asian“, 2.8% “Multiple“, <1% Unknown/Other; - Townsend: ~−2.1 to −2.4; - Education: 43% university/college; Selection data: Excluded those with or who: < 2 diet assessment; missing data on diet/covariates; implausible/extreme TEI; Dx of Cx | DP Age(s):56.1y, mean across PDI quintiles (range: 37–73y at baseline); DP and DP Components: Plant-Based Diet Index - healthful (hPDI)/unhealthful PDI (uPDI), modified [modified Satija, 2016; UK BIOBANK did not include data on vegetable oils)]; mhPDI: Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Tea/coffee; Negative: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; muPDI: Negative: Whole grains; Fruits; Vegetables; Nuts; Legumes; Tea/coffee; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; Positive: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; DP Method(s): Index/Score Analysis | Follow-up: 10.6 to 12.2y, mean; [underlined: Risk of Postmenopausal BCx]; hPDI; Q2, HR: 1.07 (0.89, 1.28); Q3, HR: 1.07 (0.89, 1.28); Q4, HR: 0.99 (0.83, 1.19); p-corrected=0.61; uPDI; Q2, HR: 1.07 (0.91, 1.26); Q3, HR: 1.07 (0.90, 1.26); Q4, HR: 1.16 (0.97, 1.38); p-corrected=0.23 | - Did not account for: Screening; - Diet assessment: 24-hr recalls, web-based; - Outcomes: Incident cases identified via registry (information center) and/or medical records; CX defined by ICD codes; - Cases identified: n=1083 postmenopasual BC; n=959 CRC; - Data NR for overall PDI & Cx risk; - Funding: Wellcome Trust medical charity, Medical Research Council, Department of Health, Scottish Government, and the Northwest Regional Development Agency; Medical Research Council, Dept. of Health Scottish Government; Welsh Assembly Government; British Heart Foundation, Diabetes United Kingdom, the Northwest Regional Development Agency.
van den Brandt, 2023 ^23^; The Netherlands; Netherlands Cohort Study (NLCS); Analytic N=62573; Participant characteristics:; - BMI, mean: 23.8 to 27; - Smokers: 2–83% never; 11–17% ever HRT; - NR (Dutch); - NRNR; Selection data:Excluded those with or who: missing data/unreliable diet; Hx of Cx | DP Age(s):61y, ~mean (55 to 69y at baseline); DP and DP Components: Alternate Mediterranean diet score (aMED) [Fung, 2005]aMED, Positive: Vegetables (not potatoes); Legumes; Fruit; Nuts; Whole Grains; Fish/Shellfish; MUFA/SFA. Negative: Red and Processed Meat. Neutral: Alcohol; DP Method(s): Index/Score Analysis; Factor/Cluster Analysis | Follow-up: 20.3y; [underlined: Risk of BCx, all postmenopausal]; aMED & overall BC (95% CI); 4–5, HR: 0.84 (0.72, 0.98); 6–8, HR: 0.88 (0.73, 1.08); p-trend=0.092 aMED & ER+ PR+; 4–5, HR: 0.86 (0.70, 1.07); 6–8, HR: 0.91 (0.69, 1.20); p-trend=0.342; aMED & ER− PR−; 4–5, HR: 0.79 (0.55, 1.14); 6–8, HR: 0.62 (0.37, 1.02); p-trend=0.050; aMED & ER+ PR−; 4–5, HR: 0.74 (0.52, 1.03); 6–8, HR: 0.80 (0.51, 1.25); p-trend=0.183; aMED & ER+; 4–5, HR: 0.80 (0.67, 0.96); 6–8, HR: 0.86 (0.68, 1.09); p-trend=0.085; aMED & ER−; 4–5, HR: 0.89 (0.65, 1.21); 6–8, HR: 0.59 (0.38, 0.92); p-trend=0.024; aMED & PR+; 4–5, HR: 0.87 (0.70, 1.08); 6–8, HR: 0.90 (0.68, 1.19); p-trend=0.321; aMED & PR−; 4–5, HR: 0.76 (0.58, 0.99); 6–8, HR: 0.74 (0.52, 1.05); p-trend=0.046; Summary: Inverse: aMED & ER+; ER−; PR−; NS/Inverse: overall BC; ER+ PR+; ER− PR−; ER+ PR−; PR+ | - Did not account for: Screening; - Diet assessment: FFQ; - Outcomes: Incident cases identified via registry (information center) and/or medical records; CX defined by ICD codes; - Cases identified: n=2321; - Analysis for ER−PR+ sub-type not possible due to sample size; - Funding: None reported
Yiannakou, 2023 ^25^; United States; Framingham Offspring; Analytic N=1579; Participant characteristics:; - BMI, mean: 25.9 to 27.2; - Smoking pack years: ~9–18; 41–50% estrogen users; - 100% Caucasian; - Education: ~20–33% at least high-school; Selection data: Excluded those with or who: were male; missing covariates; missing/incomplete/invalid FFQ; Hx or Dx of Cx; missing hormone receptor status | DP Age(s):52–56y, mean; DP and DP Components: Mediterranean Diet Score (MDS) [Trichopolou 2003], Positive: Vegetables; Legumes; Fruit, Nuts; Cereals; Fish; MUFA/SFA. Negative: Red and Processed Meat; Dairy Products. Neutral: Alcohol; Alternate Mediterranean diet score (aMED) [Fung, 2005], Positive: Vegetables (not potatoes); Legumes; Fruit; Nuts; Whole Grains; Fish/Shellfish; MUFA/SFA. Negative: Red and Processed Meat. Neutral: Alcohol; Mediterranean-based Diet Score (MedDietScore) [Panagiotakos 2007] (“MeDiet“) Positive: Vegetables; Potatoes; Legumes; Fruit; Whole Grains; Fish; Olive Oil. Negative: Red and Processed Meat; Poultry; Full-Fat Dairy; Alcohol; Mediterranean-Style Dietary Pattern Score (MSDPS) [Rumaswas 2009], Positive: Vegetables; Potatoes and Other Starchy Foods; Olives, Pulses and Nuts; Fruit (including juice); Whole Grains; Fish and Other Seafood; Poultry; Eggs; Dairy (low and full fat); Olive and other Veg. Oil; Negative: Red and processed meats; Sweets; Moderate: Wine (1.5 serv/d); No use of olive oil (0 points); DP Method(s): Index/Score Analysis | Follow-up: 18y, median; [underlined: Risk of Postmenopausal BCx]; MDS; Moderate, HR: 0.81 (0.48, 1.38); High, HR: 1.18 (0.66, 2.09); p-trend 0.46; aMED; Moderate, HR: 0.92 (0.54, 1.57); High, HR: 0.99 (0.55, 1.77); P-trend 0.96; MedDietScore (“MeDiet“); Moderate, HR: 0.68 (0.41, 1.15); High, HR: 0.58 (0.32, 1.06); P-trend 0.07; MSDP; Moderate, HR: 0.76 (0.45, 1.31); High, HR: 0.59 (0.34, 1.02); P-trend 0.06 | - Did not account for: SEP, Screening, Postmenopausal hormone therapy; - Diet assessment: FFQ; - Outcomes: Incident cases identified via self-report, medical records a/o NDI; confirmed via medical records/pathology (ER/PR status) via physician; BC defined via ICD codes;; - Cases identified: n=87; - Funding: NHLBI

a Abbreviations: [Abbreviation: Term Spelled Out; Abbreviation: Term Spelled Out]

Table 7 Evidence examining dietary patterns consumed by adults and older adults and risk of premenopausal breast cancer

Article Information | Dietary pattern (DP) intervention/exposure and comparator | Premenopausal breast cancer Results^*^; * All effect estimates (Hazard ratio, HR) and confidence intervals (CI) are reported as HR (95% CI), unless otherwise noted; Reference groups are the lowest dietary pattern category, HR: 1, unless otherwise noted | Methodological considerations
Arthur, 2020 ^1^; United Kingdom; UK BIOBANK; Analytic N=146326; Participant characteristics:; - Cases v. non-cases: BMI 18.5 to 24.9: 49% v. 50%; WC <80 cm: 53% vs. 52%; - ~55–63% never smokers; - Family Hx of BCx, 10 to 15.5%; - 100% European ancestry; - ~21% of participants in lowest quintle of Townsend deprivation index (similar across cases vs. noncases); Selection data: Excluded men, outliers for heterozygosity or missing genotype; discordant genotype vs. reported sex; putative sex chromosome aneuploidy; unknown tumor behavior; with Cx Hx; non-Eurpoean ancestry; underweight; missing lifestyle or genetic factors unknown menopausal status with no info on hysterectomy or oophorectomy | DP Age(s): 45–46 y premenopausal; DP and DP Components: modified WCRF/AICR Score - Diet only [Shams-White, 2019], mWCRF/AICR, Positive: Fruits & Vegetables; Whole grains. Negative: Red meat; Processed meat; DP Method(s): Index/Score Analysis | Follow-up: 7.1 years (median); IQR 6.3–7.7; [underlined: Risk of Premenopausal BCx]; 0 pts, HR: 1.00, ref; 1 pt, HR: 1.06 (0.90, 1.26); 2 pts, HR: 0.67 (0.51, 0.89); p-trend=0.06 | - Did not account for: None; - Diet assessment: FFQ at baseline; - Outcomes: Incident cases determined by linkage to national cancer registries in England, Wales, Scotland & death registries; - BCx cases, n=3422 (n=706 premenopausal; n=2716 postmenopausal); - Diet score is component of overall Healthy Lifestyle Index; - Funding: Breast Cancer Research Foundation
Castelló, 2024 ^2^; Spain; European Prospective Investigation into Cancer and Nutrition (EPIC)-Spain; Analytic N=24892; Participant characteristics:; - BMI, mean: 27.48;; - Smokers: 71% never; ~5% Family Hx of Cx; 9% HRT; - NR; - Education: 79% primary school or less/none (39% none, 40% primary, 11% secondary, 10% univesity+); Selection data: Excluded those with BMI of 60+; implausible/extreme TEI; first y of F/U; missing covariate data | DP Age(s):47.6y (median) at entry (IQR: 41.2–54.8y); DP and DP Components: “Western” DP: high intakes of high-fat dairy products, processed meat, refined grains, sweets, caloric drinks, convenience food and sauces [e.g., crackers, snacks, egg derivatives; processed white/blue fish]; Low intakes of low-fat dairy products and whole grains;; “Prudent” DP: high intakes of low-fat dairy products, vegetables, fruits, whole grains and [veg./fruit] juices; “Mediterranean” DP: high intakes of fish, vegetables, legumes [Peas, lentils, chickpeas, beans and broad beans], boiled potatoes, fruits, olives, and vegetable oil; Low intake of [veg./fruit] juices; DP Method(s): Factor/Cluster Analysis: PCA | Follow-up: 17.02y, median; [underlined: Risk of Premenopausal BCx]; Western; Q2, HR: 0.83 (0.5, 1.36); Q3, HR: 1.48 (0.94, 2.32); Q4, HR: 1.13 (0.69, 1.84); p-trend=0.231; per-SD, HR: 1.07 (0.9, 1.28); Prudent DP; Q2, HR: 1.02 (0.65, 1.61); Q3, HR: 1.16 (0.75, 1.81); Q4, HR: 0.76 (0.47, 1.25); p-trend=0.422; per-SD, HR: 0.96 (0.82, 1.14); Mediterranean DP; Q2, HR: 1.2 (0.8, 1.81); Q3, HR: 0.88 (0.57, 1.38); Q4, HR: 0.77 (0.46, 1.3); p-trend=0.219; per-SD, HR: 0.9 (0.76, 1.07) | - Did not account for: Race/Ethnicity, Screening, Postmenopausal hormone therapy (BC only); - Diet assessment: Diet Hx questionnaire; - Outcomes: Incident cases identified by cancer and registry linkage; definined by ICD via first occurrence of primary malignant tumor of the breast (Intrinsic sub-types classifed by pathology via ASCO/CAP guidelines: ER+, PR+, HER2−; HER2+ (irrespective of ER/PR); TN (triple negative, ER−, PR−, HER2−);; - n=639 cases BCx identified; - Intakes of dairy and fish were distributed using a set of weights due to differences in food supply from 1192 (EPIC) and 2006 (EPiGEICAM); first y of f/u excluded to minimize risk of reverse causality; - Funding: Alcala de Henares and Autonomous community of Madrid; International Agency for Research on Cancer; Department of Epidemiology and Biostatistics, School of Public Health, Imperial College London; Health Research Fund—Instituto de Salud Carlos III, the Regional Governments of Andalucía, Asturias, Basque Country, Murcia and Navarra, and the Catalan Institute of Oncology (Spain)
Chang, 2023 ^4^; United Kingdom; UK BIOBANK; Analytic N=197426; Participant characteristics:; - BMI, Overweight: 41%; Obesity 21%; - 4% CVD; 4% DM; 26% High-BP; Smokers: 57% never; 36% Family Hx of Cx; 37% HRT “ever” (♀); - 95% White, 0.5% Mixed; 1.4% South Asian; 1.2% Black; 1% Chinese or other; - Education: 43% university/college (13% A/AS; 25% O; 10% vocational; 8% not listed); Selection data: Excluded those with or who: were pregnant/unsure, implausible/extreme TEI; <1 24-hr recall; pre-existing Cx | DP Age(s):58y, mean (SD: 8) (40–69y at baseline); DP and DP Components: UPF, Nova Classification System Group 4 [Monteiro, 2019]UPF, Nova4 (Table 1, Q4 > Q1 intakes): Higher intakes of Processed Meat; Total Fat; Total Carbohydrates; Total Sodium; Lower intakes of Vegetables; Fruit; Red Meat; Alcohol; UPF, Nova4 (Fig. 1 top sources): Carbonated drinks; Fruit-based drinks; Ready-to-eat/heat foods; Industrial-processed breads; Dairy-based drinks; Pastries, buns, cakes; Sausage and other reconstituted meat products; Other beverages; Industrial-processed desserts; Sauces and spreads; Biscuits; Breakfast cereals; Confectionary; Packaged salty snacks; Alcoholic drinks; Sweeteners; Meat alternatives; Lower in Tea, Coffee; Fruit, Vegetables; Fruit juice; Beer and Wine; Cheese; DP Method(s): Index/Score Analysis | Follow-up: 9.8y, median; [underlined: Risk of Premenopausal BCx]; Nova 4; per-10%, HR: 1.00 (0.94, 1.07); Q2, HR: 1.05 (0.81, 1.36); Q3, HR: 0.98 (0.76, 1.27); Q4, HR: 1.11 (0.86, 1.44); p-trend=0.49 | - Did not account for: Screening Diet assessment: 24-hr recalls, web-based ( 1 to 6); - Outcomes: Incident cases identified registry linkage; Cx defined by ICD codes; - n= 15921 Cx cases identified (BC: n=3030; CRC: n=1670, Color n=1091, rectum n=579); - Funding: Cancer Research UK; World Cancer Research Fund (WCRF) UK
Gardeazabal, 2020 ^8^; Spain; SUN; Analytic N=10713; Participant characteristics:; - BMI, mean: ~22.2; - <2% DM; Smokers: 48–53% never; ~33–38% current HRT; 78–95% premenopause; - Spanish; - Education, mean at university: ~5y; Selection data: Excluded those with or who: were male, pre-existing BC, invalid TEI; menopause < age 35y | DP Age(s):34.5y, mean (SD: 10.8); DP and DP Components: “Western” DP: high intakes of high-fat dairy products, processed meat, refined grains, sweets, caloric drinks, convenience food and sauces [e.g., crackers, snacks, egg derivatives; processed white/blue fish]; Low intakes of low-fat dairy products and whole grains;; “Mediterranean” DP: high intakes of fish, vegetables, legumes [Peas, lentils, chickpeas, beans and broad beans], boiled potatoes, fruits, olives, and vegetable oil; Low intake of [veg./fruit] juices; DP Method(s): Factor/Cluster Analysis: PCA | Follow-up: 10.3y, median; [underlined: Risk of Premenopausal BCx]; “Western”; Q2, HR: 0.94 (0.44, 2.02); Q3, HR: 1.04 (0.48, 2.27); Q4, HR: 1.64 (0.77, 3.51); p-trend=0.209; “Mediterranean”; Q2, HR: 0.3 (0.13, 0.72); Q3, HR: 0.34 (0.14, 0.84); Q4, HR: 0.33 (0.12, 0.91); p-trend=0.055 | - Did not account for: Race/Ethnicity, Screening; - Diet assessment: FFQ; - Outcomes: Incident cases identified by self-report, verified by physicians and/or medical records as confirmed or probable; NDI if needed; Cx defined by ICD codes;; - BC cases identified: n=500; CRC cases identified: n=197; - Similar results were reported when examining only probable cases of BC (main analyses use confirmed cases); - Funding: Spanish Instituto de Salud Carlos III (ISCIII)/CIBEROBN (the Centro de Investigac on Biomedica en Red de Fisiopatologıa de la Obesidad y Nutricion), which are funded by FEDER/Spanish Government; Navarra Regional Govt.; University of Navarra
Maimaitiyiming, 2023 ^10^; United Kingdom; UK BIOBANK; Analytic N=114289; Participant characteristics:; - BMI, mean: 25–28.5; - 17–27% HTN, 2–7% DM; 2–6% CVD; Smokers: 49–62% never; ~33–36% current HRT; - ~100% White; - Townsend: ~−1.48 to −1.77;; - Education: 84–94% higher/degree; Selection data: Excluded those with or who: <1 diet assessment; Dx of Cx; implausible/extreme TEI; withdrew | DP Age(s):~56y, mean across DP quartiles (40–69 y at baseline); DP and DP Components: “Obesity-related” DP characterized by: Higher intake of beer and cider, processed meat, high-sugar beverages, red meat, and artifcial sweetener (Other positive loadings, 0.40 to 0.10: Crisps, chips, savory snacks; instant coffee; spirits/liquors; ice cream; frozen vegetable; egg and egg dishes; added sugars; breaded meat/fish; buns, cakes etc.; white bread; poultry; other breakfast cereals; PUFA margarine; boiled/baked potato; liver; legumes); Lower intake of fresh vegetables, olive oil, tea, and high fber breakfast cereals (Other negative loadings, −0.20 to 0.0: water; other milk; nuts and seeds; fruits; cereals; meat alternatives; oily fish; whole grain cereals; low-fat butter; other coffee; other fish; low-fat cheese; wine); DP Method(s): RRR | Follow-up: 9.4y, median; [underlined: Risk of Premenopausal BCx]; “Obesity-related” DP; linear, HR: 0.97 (0.92,1.02); Q2, HR: 0.90 (0.81,1.00); Q3, HR: 1.06 (0.95,1.18); Q4, HR: 0.84 (0.73,0.96); p=0.237; Complete-case, HR: 0.93 (0.88, 0.99); p=0.029 | - Did not account for: Screening; - Diet assessment: 24-hr recalls, web-based; - Outcomes: Methods NR; Cx defined by ICD; - CRCx, n=1218; Premenopausal BCx, n=809; postmenopausal BCx, n=1190; - Results also reported excluding first 2y F/U and stratified by sex; age; smoking; physical acivity; DM; HTN; CVD; - Funding: None reported for study
Peila, 2022 ^13^; United Kingdom; UK BIOBANK; Analytic N=105680; Participant characteristics:; - BMI, mean: 22.4–22.8 (all 18.5 - <25.0); - <2% DM;; - Smokers: <11% never; current HRT varied:; - ~3% premenopausal; - ~11–17% postmenopausal; - 93–97% White; - Townsend: ~−1.4 to −1.9; Selection data: Excluded those with or who: missing diet assessment; Dx of Cx; withdrew/LFU | DP Age(s):~46y (premenopausal); ~60y (postmenopausal) (40–69 y at baseline); DP and DP Components: Healthy lifestyle index (HLI)-diet only [Author, 2020 adapted WCRF/AICR score of Romaguera 2012], diet only, Positive: Vegetables, Fruit; Whole grains. Negative: Red Meat; Processed Meat; Alcohol; DP Method(s): Index/Score | Follow-up: 7y, mean (SD: 1.1); [underlined: Risk of Premenopausal BCx]; HLI-diet only; 2, HR: 0.85 (0.69,1.05); 3, HR: 0.81 (0.61,1.06); p-trend=0.049 | - Did not account for: Race/Ethnicity (93–97% White), Screening, Postmenopausal hormone therapy; - Diet assessment: 24-hr recalls, web-based; - Outcomes: Incident cases identified via national health services/information center; CX defined by ICD codes; - Cases of BCx identified: n=1796; Postmenopausal, n=1,236; Premenopausal, n=560); - Funding: Advertisement “The costs of publication of this article were defrayed in part by the payment of page charges. This article must therefore be hereby marked advertisement in accordance with 18 U.S.C. Section 1734 solely to indicate this fact””
Romanos-Nanclares, 2022 ^15^; United States; NHS; NHS II; Analytic N=0; Participant characteristics:; - BMI, mean: ~ 23 to 26.5, (range NHS & NHSII); - WC, cm, mean: ~75.2 to 82.7; - Hx of DM: ~0.6 to 6%; - Family Hx of BC: ~8% NHS, ~6% NHSII; - Biopsy-confirmed benign breast disease: 25–28% NHS; 9–10% NHSII; - Oral contraceptive use: ~49.5% NHS, ~84–85% NHSII; - Postmenopausal: ~48% NHS, ~3% NHSII; - Postmenopausal HRT, never: ~52% NHS; 7% NHSII; - 95–97% White; - SEP NR, 100% health professionals; Selection data: Excluded those with: missing values for EDIH; Cx (except nonmelanoma skin Cx); implausible baseline TEI (< 600 or > 3500 kcal/d) | DP Age(s):36 to 52y [49.2 to 52.3 (range: 38–63y), NHS I; 36 to 37.5y (range: 27–44y), NHS II]; DP and DP Components: Empirical dietary index for hyperinsulinemia (EDIH) [Tabung, 2016], Negative: Green leafy vegetables; Whole fruit; High-fat dairy products; Coffee; Wine; Positive: Red meat; Processed meat; Poultry; Tomatoes; French fries, Fish (other than dark-meat fish); Low-fat dairy; Eggs; High-energy beverages (cola and other carbonated beverages with sugar, fruit drinks); Low-energy beverages; Margarine; Cream soups;; DP Method(s): Index/Score Analysis | Follow-up: 26 to 32y; [underlined: Risk of Premenopausal BCx]; EDIH & Invasive BC; Q2 HR: 0.98 (0.86, 1.12); Q3 HR: 1.04 (0.91, 1.19); Q4 HR: 1.04 (0.90, 1.19); Q5 HR: 1.07 (0.91, 1.25); P-trend =0.34; EDIH & ER-negative; Q2 HR: 0.84 (0.60, 1.17); Q3 HR: 1.00 (0.72, 1.39); Q4 HR: 1.05 (0.75, 1.47); Q5 HR: 1.01 (0.70, 1.47); P-trend =0.67 | - Did not account for: Smoking, Screening; - Diet assessment: FFQ every 4 y; - Outcomes: Incident cases identified via medical record review and self-reported cases confirmed by the nurse; luminal A tumors: ER-positive and/or PR-positive, HER2-negative, and Ki-67-negative (or histologic grade 1 or 2); luminal B tumors: either ER-positive and/or PR-positive and HER2-positive or 2) ER-positive and/or PR-positive, HER2-negative, and Ki-67-positive (or histologic grade 3); HER2-enriched tumors: ER− negative, PR-negative, and HER2− positive; Basal-like tumors: ER− negative, PR-negative, HER2− negative, and CK 5/6-positive and/or EGFR-positive; ER status determined from TMA slides, and secondarily from pathology; - Additional analyses on Basal-like tumors, Insulin receptor −/+ and adjusted for consumption of food groups; lag analysis; interaction between EDIH and current BMI, physical activity, total alcohol intake and; - Funding: NIH, Breast Cancer Research Foundation, Ramon Areces Foundation and Susan G Komen Foundation
Romanos-Nanclares, 2020 ^16^; Spain; SUN; Analytic N=10812; Participant characteristics:; - BMI, kg/m2: ~22.2; - PA, METs-h/week: 19.9–20.6; - Diabetes, %: 0.94 –1.34; - Smoking, Never: 48.8–53.9%; - Family history of BCx: ~11%; - Postmenopausal, %: 9.4–14.0; - Postmenopausal ≥ 50 y, %: 47; - Spanish; - Education: ~4.8 y university; Selection data: Excluded those who were recruited after 2015 October, LFU, prevalent BC, TEI outside predefined limits, or reported menopause at age < 35 y | DP Age(s):~35y, mean; DP and DP Components: Provegetarian Food Pattern [Martinez-Gonzalez 2014], Positive: Vegetables; Potatoes; Legumes; Fruits; Nuts; Cereals; Vegetable fat; Pastries; Sugar-sweetened beverages; Coffee. Negative: Fish and Other Seafood; Meats and Meat Products; Eggs; Dairy Products; Animal Fats for cooking or as a spread; Healthy PVG, fitted from hPDI [Satija, 2016], Positive: Vegetables; Boiled or Baked Potatoes; Legumes; Fruits; Nuts; Whole Grains; Vegetable oil and Coffee; Negative: Pastries; Refined Grains; French Fries; Sugar-sweetened beverages; Fish and Other Seafood; Meats and Meat Products; Eggs; Dairy; Products; Animal Fats for cooking or as a spread; Other Vegetable Fats; Unhealthy PVG, fitted from uPDI [Satija, 2016], Negative: Vegetables; Boiled or Baked Potatoes; Legumes; Fruits; Nuts; Whole Grains; Vegetable oil and Coffee; Negative: Pastries; Refined Grains; French Fries; Sugar-sweetened beverages; Fish and Other Seafood; Meats and Meat Products; Eggs; Dairy; Products; Animal Fats for cooking or as a spread; Other Vegetable Fats; DP Method(s): Index/Score Analysis | Follow-up: 11.5y, median; [underlined: Risk of Premenopausal BCx]; PVG; T2: HR 0.40 (0.19, 0.86); T3: HR 0.89 (0.50, 1.58); P for trend=0.441; hPVG; T2: HR 1.02 (0.55, 1.90); T3: HR 0.79 (0.40, 1.57); P for trend=0.503; uPVG; T2: HR 1.14 (0.60, 2.15); T3: HR 1.09 (0.56, 2.13); P for trend=0.807 | - Did not account for: Race/Ethnicity (Spanish), Screening; - Diet assessment: FFQ; - Outcomes: Incident cases identified via self-reported Dx and confirmed by physician medical record review; - Additional analyses with probable incident BC cases but results hardly changed; changing energy limits;; - Limited generalizibility; self-reported case; one-time diet measurement; - Funding: the Spanish Government-Instituto de Salud Carlos III, the European Regional Development Fund, and the University of Navarra
Romanos-Nanclares, 2021 ^17^; United States; NHS; NHSII; Analytic N=0; Participant characteristics:; - BMI, kg/m2: ~25.0 NHS; 23.7–25.2 NHSII; - Hx of T2D: 2–4% NHS; ~1% NHSII; - Family Hx BC: 8% NHS; 6% NHSII; - Personal Hx benign breast disease: ~30% NHS; ~10% NHSII; - Postmenopausal: ~48.5% NHS; 3.2% NHSII; - African heritage: ~1.1–1.5% in NHS; 1.2 –2.0% in NHSII; - SEP NR; 100% health professionals; Selection data: Excluded women who died prior to baseline, had prevalent cancer, had missing dietary information, or reported implausible TEI | DP Age(s): 50y, ~ mean NHS; 37y, ~ mean NHS II; DP and DP Components:; modified Plant-Based Diet Index (mPDI), healthful/unhealthful PDI (mhPDI/muPDI) [Kim 2022 modified Satija, 2016 - removed vegetable oils (margarine) and alcohol from score]; mPDI: Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Tea/coffee; Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Negative: Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; mhPDI: Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Tea/coffee; Negative: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; muPDI: Negative: Whole grains; Fruits; Vegetables; Nuts; Legumes; Tea/coffee; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; Positive: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; DP Method(s): Index/Score Analysis | Follow-up: 32y NHS; 26 y NHSII; [underlined: Risk of Premenopausal BCx]; PDI & ER−, per 10 units, HR 0.86 (0.72, 1.03); hPDI & ER−, per 10 units, HR 0.87 (0.74, 1.02); uPDI & ER−, per 10 units, HR 1.13 (0.98, 1.32) | - Did not account for: Smoking, Screening; - Diet assessment: FFQ at baseline (collected every 4 y); - Outcomes: Incident cases identified via self-report and confirmed via medical record review or nurse; subtypes based on gene expression profiles; - Cohort-specific analyses showed similar results as overall; Results slightly attenuated adjusting weight change since age 18 for PDI; adjusting weight change, total carotenoid intake for hPDI; adjusting dietary fiber did not change the results;; - Funding: NIH, the Breast Cancer Research Foundation; Spanish Association Against Cancer Scientific Foundation
Shin, 2020 ^21^; Korea; Health Examinees-Gem (HEXA-G), part of Korean Genome and Epidemiology Study (KoGES); Analytic N=78320; Participant characteristics:; - BMI, mean: 23.6; - Smokers: 4% Ever; - Korean; - Education: 20% college+; 87% Cohabitaing; Selection data: Excluded those with or who: missing data/unreliable diet; Dx of Cx | DP Age(s):52.3y, mean; DP and DP Components: “Meat” DP; “White rice” DP; “Other” DP“Meat” DP: high intakes of bread, pizza and hamburger, cereals and snacks, noodles, dumplings, red meat, red meat by-products, poultry, eggs; processed meat and fish; other seafood; dairy products; tea; “White rice” DP: high intakes of white rice and salt-fermented fish and lower intake of multi-grain rice, tubers (potatoes and sweet potatoes), nuts; legumes and soybean paste, tofu, and milk; “Other” DP: high intakes of yellow-green vegetables, other vegetables, potatoes and sweet potatoes, mushrooms, seaweed, lean fish, fatty fish, shellfish, dried anchovy, legumes and soybean paste, tofu; starch jelly; kimchi; pickled vegetables; fruit and fruit juices; red meat; eggs; other seafood; processed meats and dishes; milk; dairy products; DP Method(s): Factor/Cluster Analysis: PCA | Follow-up: 6.3y, mean; [underlined: Risk of Premenopausal BCx]; “Meat” DP; Q2, HR: 0.70 (0.51, 0.97); Q3, HR: 0.99 (0.73, 1.33); Q4, HR: 1.05 (0.76, 1.47); p-trend=0.305; “White rice” DP; Q2, HR: 1.14 (0.84, 1.55); Q3, HR: 1.00 (0.72, 1.40); Q4, HR: 1.35 (1.00, 1.84); p-trend=0.038; “Other” DP &; Q2, HR: 1.12 (0.82, 1.54); Q3, HR: 1.18 (0.86, 1.61); Q4, HR: 1.30 (0.94, 1.80); p-trend=0.122 | - Did not account for: Race/Ethnicity (Korean), Screening, Postmenopausal hormone therapy (all were age <50y at baseline); - Diet assessment: FFQ; - Outcomes: Incident cases identified via linkage with registry and verified; CX defined by ICD codes; - Cases identified: n=359 BC; - Funding: Korea Centers for Disease Control and Prevention

Table 8 Risk of bias for randomized controlled trial examining dietary patterns consumed in adults and older adults and breast cancer^a^

Article | Randomization | Deviations from intended interventions (effect of assignment) or (per-protocol) | Missing outcome data | Outcome measurement | Selection of the reported result | Overall risk of bias
Chlebowski, 2020^6^ | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS

a Possible ratings of low, some concerns, or high determined using the "Cochrane Risk-of-bias 2.0" (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2019 version)” ( Sterne JAC, Savović J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ 2019; 366: l4898.31462531

Table 9 Risk of bias for observational studies examining dietary patterns consumed in adults and older adults and breast cancer^a^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Arthur, 2023^1^ | LOW | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Castelló, 2024^2^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Chaltiel, 2022^3^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | LOW | LOW | HIGH
Chang, 2023^4^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Chebet, 2020^5^ | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | LOW | LOW | LOW | HIGH
Dela Cruz, 2020^7^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Gardeazabal, 2020^8^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Jin, 2023^9^ | SOME CONCERNS | SOME CONCERNS | LOW | SOME CONCERNS | LOW | LOW | SOME CONCERNS | HIGH
Maimaitiyiming, 2023^10^ | SOME CONCERNS | LOW | LOW | LOW | HIGH | SOME CONCERNS | SOME CONCERNS | HIGH
Männistö, 2021^11^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Neuhouser, 2022^12^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | HIGH
Peila, 2022^13^ | HIGH | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | HIGH
Petermann-Rocha, 2021^14^ | HIGH | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | HIGH
Romanos-Nanclares, 2022^15^ | HIGH | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS | HIGH
Romanos-Nanclares, 2020^16^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Romanos-Nanclares, 2021^17^ | HIGH | SOME CONCERNS | LOW | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | HIGH
Shah, 2023^18^ | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS
Shah, 2023^19^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS
Shang, 2023^20^ | HIGH | LOW | LOW | LOW | SOME CONCERNS | LOW | LOW | HIGH
Shin, 2020^21^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | LOW | SOME CONCERNS
Thompson, 2023^22^ | SOME CONCERNS | LOW | LOW | LOW | LOW | LOW | HIGH | HIGH
van den Brandt, 2023^23^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Willemsen, 2022^24^ | VERY HIGH | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | HIGH | VERY HIGH
Yiannakou, 2023^25^ | HIGH | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS | HIGH
Zhu, 2023^26^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | LOW | LOW | HIGH | HIGH

a Possible ratings of low, some concerns, high, very high, no information, or not applicable were determined using the "Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)" tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602. ) *Low risk of bias except for concerns about uncontrolled confounding.