# Appendix 6 Dietary pattern visualization

The Committee’s synthesis was facilitated by data visualization tables that presented the dietary pattern components in each of the dietary patterns examined in the body of evidence. During evidence synthesis, these tables were used in conjunction with other materials to compare and contrast the components between and within the dietary patterns studied along with the direction, magnitude, and statistical significance of reported results. Detailed information about the body of evidence, including study and population characteristics, a full description of each dietary pattern, reported results for all relevant outcomes, key confounders accounted for, study limitations, and funding sources, are summarized in the evidence tables of this report (Table 6; Table 7). Each column represents the most commonly reported foods/food groups or nutrients across dietary patterns in this body of evidence. One additional column, “Other”, captured a variety of other components less frequently reported across dietary patterns that did not fit into one of the preceding columns or categories, such as fast food, ready-to-eat dishes, pizza, and chocolate. Multiple symbols in each cell mean that the dietary pattern included multiple components from that column/category. Empty cells mean that the dietary pattern did not describe a component within that column/category.

Table A 8 Visualization of dietary pattern components organized by first-author last name alphabetically across evidence examining the relationship between dietary patterns consumed and risk of breast cancer^*^ * ▲ Positively-scored component, reflecting higher intake within the food category as part of the pattern; ▼ Negatively-scored component, reflecting lower intake within the food category as part of the pattern; ◄ Neutral component, reflecting moderate (in contrast to higher or lower) intake within the food category as part of the pattern ^†^ † Abbreviations: AF, added fat; AP, animal-based foods and products; C, coffee only; ch, cheese; D, dairy and dairy products; F, fish; Fer., Fermented; FF, fried potato or French fries; Fr, included with the Fruit component; Fr,V, fruits and vegetables; FS, fish and seafood; G, grains or cereals; HF, high-fiber; LN, legumes and nuts; M, meat and meat products; Med, Mediterranean; Na+, sodium; NP, not processed; NS, not sweetened; oo, olive oil; P, processed; pro, protein; RP, red and processed; SB, sugar-sweetened beverage; T, tea only; tom, tomatoes; Tr, trans-fat; UF: SF, ratio of unsaturated relative to saturated fat; UP, ultra-processed; vegetable; VO; vegetable oils; W: R, white-to-red meat ratio; X, component was excluded from the dietary pattern; y, yogurt

Article; Approach: Dietary pattern^‡^; ‡ Dietary approaches included methods such as a priori index/score analysis and investigator-assigned dietary intervention (RCT), a posteriori principal component analysis (PCA), and reduced rank regression (RRR). The dietary pattern is abbreviated in this table due to limited space but is described in more detail in Table 6 and Table 7 of the main document. | Vegetables | Potato | Other Vegetables | Legumes | Fruit | Fruit Juice | Nuts, Seeds | Grains: Whole | Grains | Grains: Refined | Fish | Seafood, shellfish | Meats (Red Processed) | Lean Ms (Poultry) | Eggs | Dairy | Dairy: Low, non-fat | Dairy: Whole, high fat | Sugary Beverages | Sugary foods | Fat: Unsaturated | Fat: Other | Fat: Saturated | Alcohol | Sodium | Tea and Coffee | Other
Arthur, 2020; a priori: mWCRF, AICR score | ▲ | | | | V | | | ▲ | | | | | ▼ RP
Castelló, 2024; PCA: ‘Med’ | ▲ | ▲ | | ▲ | ▲ ▲ | ▼ Fr,V | ▲ | ▲ | | | ▲ | | | | | | | | | | ▲ VO
Castelló, 2024; PCA: ‘Prudent’ | ▲ | | | | ▲ | Fr,V | | ▲ | | | | | | | | | ▲
Castelló, 2024; PCA: ‘Western’ | | | | | | | | ▼ | | ▲ | ▲ | | ▲P | ▲ | F | | ▼ | ▲ | ▲ | ▲ | | | | | F
Chaltiel, 2022; a priori: PNNS-GS2 | ▲ | G | | G | V | | | | ◄ | | ◄ | ▲ FS | ◄ | ◄ | ◄ | ◄ | D | D | ▼ | ▼ | ▲ | ▼ AF | | ◄ | ▼ salt
Chang, 2023; a priori: UPF, Nova4 | ▼ | | | | | | | | | | | | ▼ R | ▲ P | | | | | | | | ▲ | | ▼ | ▲ | | ▲
Chebet, 2020; a priori: HEI-2015 | ▲ ▲L | V | | V; pro | ▲ ▲ | | | ▲ | | ▼ | ▲ pro | pro | ▲ pro | pro | | ▲ | D | D | ▼ | SB | ▲ UF: SF | | ▼ | | ▼
Chlebowski, 2020; RCT: Low-fat v. CG | ▲ | | | | ▲ | | | ▲ | ▲ | G | | | | | | | | | | | ▼ | ▼ Tr ▼ | ▼ SF | ◄ | | | ▲ ▲ ▲ ▲ pro
Dela Cruz, 2020; a priori: aMED (modified MDS) | ▲ | X | | ▲ | ▲ | X | ▲ | ▲ | | | ▲ | FS | ▼ RP | | | | | | | | ▲ UF: SF | | UF: SF | ◄
Dela Cruz, 2020; a priori: aHEI-2010 | ▲ | X | | ▲ | ▲ | | LN | ▲ | | | | | ▼ RP | | | | | | ▼ | | ▲ ▲ | ▼ Tr | | ◄ | ▼
Dela Cruz, 2020; a priori: DASHs | ▲ | X | | ▲ | ▲ | Fr | LN | ▲ | | | | | ▼ RP | | | | ▲ | | ▼ | | | | | | ▼
Dela Cruz, 2020; a priori: HEI-2015 | ▲ ▲L | V | | V; pro | ▲ ▲ | | | ▲ | | ▼ | ▲ pro | pro | ▲ pro | pro | | ▲ | D | D | ▼ | SB | ▲ UF: SF | | ▼ | | ▼
Gardeazabal, 2020; PCA: ‘Med’ | ▲ | ▲ | | ▲ | ▲ | ▲ | ▲ | ▲ | | | ▲ | | ▲R | ▲ | ▲ | | | | | | ▲ oo
Gardeazabal, 2020; PCA: Western’ | ▼ | ▲ | | | ▼ | | | ▼ | | ▲ | ▼ | | ▲R | | | | ▼ | ▲ | | | | | | | | | ▲
Jin, 2023; a priori: HEI-2015 | ▲ ▲L | V | | V; pro | ▲ ▲ | | | ▲ | | ▼ | ▲ pro | pro | ▲ pro | pro | | ▲ | D | D | ▼ | SB | ▲ UF: SF | | ▼ | | ▼
Jin, 2023; a priori: rEDIP | ▼ ▼ ▼ | | ▲ tom | | | ▼ | | | | ▲ | ▲ | | ▲P ▲R ▲ | | | | | | ▲ | | | | | | ▼ snack foods | ▼ T ▼ C | ▼
Jin, 2023; a priori: EDIH | ▼ | ▲ FF | | | ▼ | | | | | | ▲ | | ▲R ▲P | ▲ | ▲ | | ▲ | ▼ | ▲ | | | ▲ | | ▼ w | | ▼ C | ▲ ▲
Maimaitiyiming, 2023; RRR: Obesity-related’ | ▼ | ▲ | | ▲ | | ▼ | | ▼ H F | ▲ | ▲ | | | ▲ RP | ▲ | ▲ | | | | ▲ | ▲ | ▼ oo | ▲ | | ▲ fer | ▲ snack foods | ▼ T | ▲ ▲
Männistö, 2021; a priori: aMED (modified MDS) | ▲ | X | | ▲ | ▲ | | ▲ | ▲ | | | ▲ | | ▼ R | | | | | | | | ▲ UF: SF | | UF: SF | ◄
Männistö, 2021; a priori: mNDI (mBDS) | ▲ | | | V | ▲ | | | ▲ | | | ▲ | | ▼ RP | | | | ▲ | | | | ▲ UF: SF+ Tr | ▼ | UF: SF +Tr | ◄
Männistö, 2021; a priori: mAHEI | ▲ | X | | ▲ | ▲ | | LN | ▲ | | | | | W:R | ▲ W: R | | | | | ▼ | | ▲ UF: SF | ▼ Tr | UF: SF | ◄ | | | ▲
Neuhouser, 2022; a priori: HEI-2010 | ▲ ▲ | V | | V | ▲ ▲ | | | ▲ | | ▼ | ▲ pro | pro | ▲ pro | pro | | ▲ | D | D | ▼ | SB | ▲ | | ▼ | | ▼
Peila, 2022; a priori: HLI-diet, adapted WCRF/AICR | ▲ | | | | ▲ | | | ▲ | | | | | ▼R ▼P | | | | | | | | | | | ◄
Petermann-Rocha, 2021; a priori: DRS | ▼ | | | | V | | | | ▼ | | ▼ | FS | ▲R ▲P | | | | | ▲ | | | | | ▲ | | ▼ | | ▼
Romanos-Nanclares, 2020; a priori: hPVG, fitted from hPDI | ▲ | ▼ FF | | ▲ | ▲ | | ▲ | ▲ | | ▼ | ▼ | FS | ▼ | M | ▼ | ▼ | D | D | ▼ | ▼ | ▲ VO | ▼ | ▼ AP | | | ▲ C | ▲
Romanos-Nanclares, 2020; a priori: Proveg. | ▲ | ▲ | | ▲ | ▲ | | ▲ | | ▲ | | ▼ | FS | ▼ | M | ▼ | ▼ | D | D | ▲ | ▲ | ▲ VO | ▼ | ▼ | | | ▲ C
Romanos-Nanclares, 2020; a priori: uPVG, fitted from uPDI | ▼ | ▲ FF ▼ | | ▼ | ▼ | | ▼ | ▼ | | ▲ | ▼ | FS | ▼ | M | ▼ | ▼ | D | D | ▲ | ▲ | ▼ VO | ▲ | ▼ | | | ▼ C | ▼ AP
Romanos-Nanclares, 2021; a priori: mhPDI | ▲ | ▼ | | ▲ | ▲ | ▼ | ▲ | ▲ | | ▼ | ▼ | FS | ▼ | M | ▼ | ▼ | D | D | ▼ | ▼ | | | ▼ | | | ▲ | ▼ AP
Romanos-Nanclares, 2021; a priori: mPDI | ▲ | ▲ | | ▲ | ▲ | ▲ | ▲ | ▲ | | ▲ | ▼ | FS | ▼ | M | ▼ | ▼ | D | D | ▲ | ▲ | | | ▼ | | | ▲ | ▼ AP
Romanos-Nanclares, 2021; a priori: muPDI | ▼ | ▲ | | ▼ | ▼ | ▲ | ▼ | ▼ | | ▲ | ▼ | FS | ▼ | M | ▼ | ▼ | D | D | ▲ | ▲ | | | ▼ | | | ▼ | ▼ AP
Romanos-Nanclares, 2022; a priori: EDIH | ▼ | ▲ FF | ▲ tom | | ▼ | | | | | | ▲ | | ▲R ▲P | ▲ | ▲ | | ▲ | ▼ | ▲ | | | ▲ | | ▼ w | | ▼ C | ▲
Shah, 2023_Long-term; a priori: hPDI | ▲ | ▼ | | ▲ | ▲ | ▼ | ▲ | ▲ | | ▼ | ▼ | FS | ▼ | M | ▼ | ▼ | D | D | ▼ | ▼ | ▲ VO | | ▼ | | | ▲ | ▼ AP
Shah, 2023_Long-term; a priori: PDI | ▲ | ▲ | | ▲ | ▲ | ▲ | ▲ | ▲ | | ▲ | ▼ | FS | ▼ | M | ▼ | ▼ | D | D | ▲ | ▲ | ▲ VO | | ▼ | | | ▲ | ▼ AP
Shah, 2023_Long-term; a priori: uPDI | ▼ | ▲ | | ▼ | ▼ | ▲ | ▼ | ▼ | | ▲ | ▼ | FS | ▼ | M | ▼ | ▼ | D | D | ▲ | ▲ | ▼ VO | | ▼ | | | ▼ | ▼ AP
Shah, 2023_Palaeolithic; a priori: Paleo | ▲ ▲ | | | V | ▲ | | ▲ | | ▼ | ▼ | ▲ | | ▼ RP | ▲ | | ▼ | D | D | | | | | | ▼ | ▼ | | ▲
Shang, 2023; a priori: aMED | ▲ | X | | ▲ | ▲ | | ▲ | ▲ | | | ▲ | | ▼ RP | | | | | | | | ▲ UF: SF | | UF: SF | ◄
Shang, 2023; a priori: aHEI-2010 | ▲ | X | | ▲ | ▲ | | LN | ▲ | | | | | ▼ RP | | | | | | ▼ | | ▲ ▲ | ▼ Tr | | ◄ | ▼
Shang, 2023; a priori: rEDIP | ▼ ▼ ▼ | | ▲ tom | | | ▼ | | | | ▲ | ▲ | | ▲P ▲R ▲ | | | | | | ▲ | | | | | ▼ b ▼ w | ▼ snack foods | ▼ T ▼ C | ▼
Shang, 2023; a priori: hPDI | ▲ | ▼ | | ▲ | ▲ | ▼ | ▲ | ▲ | | ▼ | ▼ | FS | ▼ | M | ▼ | ▼ | D | D | ▼ | ▼ | ▲ VO | | ▼ | | | ▲ | ▼ AP
Shin, 2020; PCA: meat’ | | | | ▼ | | | | | ▲ | | ▲ | FS | ▲ RP; FS | ▲ | ▲ | ▲ | | | | ▲ | | | | | | ▲ T | ▲
Shin, 2020; PCA: other’ | ▲ ▲ ▲ | ▲ | | ▲ | ▲ | Fr | | | | | ▲ | FS | ▲ | ▲ | ▲ | ▲ | D | D | | | | | | | | | ▲
Shin, 2020; PCA: white rice’ | | ▼ | | ▼ | | | ▼ | ▼ | ▲ | | ▲ fer, salt | | | | | ▼ mil k
Thompson, 2023; a priori: hPDI, m | ▲ | ▼ | | ▲ | ▲ | ▼ | ▲ | ▲ | | ▼ | ▼ | FS | ▼ | M | ▼ | ▼ | D | D | ▼ | ▼ | ▲ VO | | ▼ | | | ▲ | ▼ AP
Thompson, 2023; a priori: uPDI, m | ▼ | ▲ | | ▼ | ▼ | ▲ | ▼ | ▼ | | ▲ | ▼ | FS | ▼ | M | ▼ | ▼ | D | D | ▲ | ▲ | ▼ VO | | ▼ | | | ▼ | ▼ AP
van den Brandt, 2023; a priori: aMED | ▲ | X | | ▲ | ▲ | | ▲ | ▲ | | | ▲ | FS | ▼ RP | | | | | | | | ▲ UF: SF | | UF: SF | ◄
Willemsen, 2022; RRR; PCA: Prudent’ | ▲ | | | | ▲ | | | | | | ▲ | FS | | ▲
Willemsen, 2022; RRR; PCA: ‘Western’ | ▲ | ▲ | | | | | | | | ▲ | | | ▲ RP | | | ▲ ch | | | ▲ | SB | | ▲
Willemsen, 2022; RRR; PCA: Dietary fiber | ▲ | | | | ▲ | | | | ▲
Willemsen, 2022; RRR; PCA: Fruits, sugar, dairy | | | | | ▲ | | | ▲ | | | | | | | | ▲ | D | D | ▲ | SB
Willemsen, 2022; RRR; PCA: Vitamin D | | | | | | | | | | | ▲ | FS | | | | ▲ | D | D
Yiannakou, 2023; a priori: aMED | ▲ | X | | ▲ | ▲ | | ▲ | ▲ | | | ▲ | FS | ▼ RP | | | | | | | | ▲ UF: SF | | UF: SF | ◄
Yiannakou, 2023; a priori: MedDietScore | ▲ | ▲ | | ▲ | ▲ | | | ▲ | | | ▲ | | ▼ RP | ▼ | | | | ▼ | | ▼ | ▲ oo | | | ▼
Yiannakou, 2023; a priori: MSDPS | ▲ | ▲ | | ▲ | ▲ | Fr | LN | ▲ | | | ▲ | FS | ▼ RP | ▲ | ▲ | ▲ | D | D | | ▼ | ▲ oo | | | ◄ w
Yiannakou, 2023; a priori: MDS | ▲ | | | ▲ | ▲ | | ▲ | | ▲ | | ▲ | | ▼ RP | | | ▼ | D | D | | | ▲ UF: SF | | UF: SF | ◄
Zhu, 2023; a priori: HDS | ▲ | | | | ▲ | | | | | | ▲ | | ▼R ▼P