# Appendix 5 Excluded articles

The following table lists the articles excluded after full-text screening for this systematic review question. At least one reason for exclusion is provided for each article, though this may not reflect all possible reasons. Information about articles excluded after title and abstract screening is available upon request.

Table A 7 List of excluded articles with rationale

Number | Citation | Rationale
1 | Aguilera-Buenosvinos I, Martinez-Gonzalez MÁ, Zazpe I, Romanos-Nanclares A, Sánchez-Bayona R, Toledo E. Associations between overall, healthful, and unhealthful low-fat dietary patterns and breast cancer risk in a Mediterranean cohort: The SUN project. Nutrition. 2023.109:111967. doi:10.1016/j.nut.2022.111967.36738657 | Intervention/Exposure
2 | Arima, K, Zhong, R, Ugai, T, Western-Style Diet, pks Island-Carrying Escherichia coli, and Colorectal Cancer: Analyses From Two Large Prospective Cohort Studies. Gastroenterology. 2022. 163:862–874. doi:10.1053/j.gastro.2022.06.054.35760086 | Outcome
3 | Aroke, D, Folefac, E, Shi, N, Inflammatory and Insulinemic Dietary Patterns: Influence on Circulating Biomarkers and Prostate Cancer Risk. Cancer Prev Res (Phila). 2020. 13:841–852. doi: 10.1158/1940-6207.Capr-20-0236 .32655006 | Outcome
4 | Arthur RS, Kirsh VA, Rohan TE, The association of the healthy eating index with risk of colorectal cancers (overall and by subsite) among Canadians. Cancer Epidemiol. 2023. 87:102454. doi:10.1016/j.canep.2023.102454.37879292 | Outcome
5 | Barrubés, L, Babio, N, Hernández-Alonso, P, Association between the 2018 WCRF/AICR and the low-risk lifestyle scores with colorectal cancer risk in the predimed study. Journal of Clinical Medicine. 2020. 9. doi:10.3390/jcm9041215. | Outcome
6 | Blackie K, Bobe G, Takata Y. Vegetarian diets and risk of all-cause mortality in a population-based prospective study in the United States. J Health Popul Nutr. 2023. 42(1):130. doi:10.1186/s41043-023-00460-9.37996932 | Intervention/Exposure
7 | Botteri, E, Peveri, G, Berstad, P, Changes in Lifestyle and Risk of Colorectal Cancer in the European Prospective Investigation Into Cancer and Nutrition. American Journal of Gastroenterology. 2023. 118(4):702-711. doi:10.14309/ajg.0000000000002065.36227801 | Intervention/Exposure
8 | Cai, H, Sobue, T, Kitamura, T, Low-carbohydrate diet and risk of cancer incidence: The Japan Public Health Center-based prospective study. Cancer Science. 2022. 113:744–755. doi:10.1111/cas.15215 .34821435 | Intervention/Exposure
9 | Castelló, A, Rodríguez-Barranco, M, Fernández de Larrea, N, Adherence to the Western, Prudent and Mediterranean Dietary Patterns and Colorectal Cancer Risk: Findings from the Spanish Cohort of the European Prospective Investigation into Cancer and Nutrition (EPIC-Spain). Nutrients. 2022. 14. doi:10.3390/nu14153085. | Outcome
10 | Castelló A, Rodríguez-Barranco M, Pérez-Gómez B, Chirlaque MD, Bonet C, Amiano P, High adherence to Western dietary pattern and prostate cancer risk: findings from the EPIC-Spain cohort. BJU Int. 2023. 132(3):272-282. doi:10.1111/bju.16001.37073612 | Outcome
11 | Chang, K, Millett, C, Rauber, F, Ultra-processed food consumption, cancer risk, and cancer mortality: a prospective cohort study of the UK Biobank. EClinicalMedicine. 2023. 356:101840. doi:10.1016/j.eclinm.2023.101840. | Publication Status
12 | Chen, SLF, Braaten, T, Borch, KB, Combined lifestyle behaviors and the incidence of common cancer types in the norwegiar women and cancer study (Nowac). Clinical Epidemiology. 2021. 13:721–734. doi:10.2147/CLEP.S312864 .34429658 | Intervention/Exposure
13 | Debras, C, Chazelas, E, Srour, B, Fermentable Oligosaccharides, Disaccharides, Monosaccharides, and Polyols (FODMAPs) and Cancer Risk in the Prospective NutriNet-Santé Cohort. J Nutr. 2022. 152:1059–1069. doi:10.1093/jn/nxab379 . | Intervention/Exposure
14 | Fraser, GE, Cosgrove, CM, Mashchak, AD, Lower rates of cancer and all-cause mortality in an Adventist cohort compared with a US Census population. Cancer. 2020. 126:1102–1111. doi:10.1002/cncr.32571 .31762009 | Intervention/Exposure
15 | Fu, BC, Tabung, FK, Pernar, CH, Insulinemic and Inflammatory Dietary Patterns and Risk of Prostate Cancer. Eur Urol. 2021. 79:405–412. doi:10.1016/j.eururo.2020.12.030.33422354 | Outcome
16 | Hoang T, Cho S, Choi JY, Kang D, Shin A. Assessments of dietary intake and polygenic risk score in associations with colorectal cancer risk: evidence from the UK Biobank. BMC Cancer. 2023. 23(1):993. doi:10.1186/s12885-023-11482-1.37853340 | Outcome
17 | Huang MC, Huang TT, Feng HC, Chen IC, Chang CI, Wang TN, Lifestyle Factors and Energy Intakes with Risks of Breast Cancer among Pre- and Post- Menopausal Women in Taiwan. Nutrients. 2023. 15(18):3900. doi: 10.3390/nu15183900.37764684 | Study Design
18 | Jacobs, I, Taljaard-Krugell, C, Wicks, M, Dietary Patterns and Breast Cancer Risk in Black Urban South African Women: The SABC Study. Nutrients. 2021. 13(11):4106. doi:10.3390/nu13114106.34836361 | Study Design
19 | Kim, J, Boushey, CJ, Wilkens, LR, Haiman, CA, Le Marchand, L, Park, S-Y. Plant-based dietary patterns defined by a priori indices and colorectal cancer risk by sex and race/ethnicity: the Multiethnic Cohort Study. BMC Med. 2022. 20(1):430. doi:10.1186/s12916-022-02623-7.36443779 | Outcome
20 | Kim J, Khil J, Kim H, Keum N, Zhang X, Giovannucci E. Plant-based dietary patterns and the risk of digestive system cancers in 3 large prospective cohort studies. Eur J Epidemiol. 2023. 38(6):617-627. doi:10.1007/s10654-023-01007-2.37101016 | Outcome
21 | Kliemann N, Rauber F, Bertazzi Levy R, Viallon V, Vamos EP, Cordova R, Food processing and cancer risk in Europe: results from the prospective EPIC cohort study. Lancet Planet Health. 2023. 7(3):e219-e232. doi:10.1016/S2542-5196(23)00021-9.36889863 | Intervention/Exposure
22 | Kresovich, JK, Park, Y-MM, Keller, JA, Healthy eating patterns and epigenetic measures of biological age. Am J Clin Nutr. 2022. 115(1):171-179. doi:10.1093/ajcn/nqab307.34637497 | Study Design; Outcome
23 | Lan, T, Park, Y, Colditz, GA, Adolescent dietary patterns in relation to later prostate cancer risk and mortality in the NIHAARP Diet and Health Study. Br J Cancer. 2023. 128(1):57-62. doi:10.1038/s41416-022-02035-7.36316560 | Outcome
24 | Leach, HJ, Baxter, BA, Beale, MN, Feasibility of Beans/Bran Enriching Nutritional Eating For Intestinal Health & Cancer Including Activity for Longevity: A Pilot Trial to Improve Healthy Lifestyles among Individuals at High Risk for Colorectal Cancer. Integr Cancer Ther. 2020. 19:1534735420967101. doi:10.1177/1534735420967101.33111581 | Outcome
25 | Lécuyer, L, Dalle, C, Lefevre-Arbogast, S, Diet-Related Metabolomic Signature of Long-Term Breast Cancer Risk Using Penalized Regression: An Exploratory Study in the SU.VI.MAX Cohort. Cancer Epidemiol Biomarkers Prev. 2020. 29:396–405. doi:10.1158/1055-9965.Epi-19-0900.31767565 | Study Design; Intervention/Exposure
26 | Lee, DH, Jin, Q, Shi, N, Dietary Inflammatory and Insulinemic Potentials, Plasma Metabolome and Risk of Colorectal Cancer. Metabolites. 2023. 13(6):744. doi: 10.3390/metabo13060744. | Outcome
27 | Liu F, Lv Y, Peng Y, Plant-based dietary patterns, genetic predisposition and risk of colorectal cancer: a prospective study from the UK Biobank. J Transl Med. 2023. 21(1):669. doi:10.1186/s12967-023-04522-8.37759216 | Outcome
28 | Loeb, S, Fu, BC, Bauer, SR, Association of plant-based diet index with prostate cancer risk. Am J Clin Nutr. 2022. 115:662 670. doi:10.1093/ajcn/nqab365.34791008 | Outcome
29 | Long, M, Wang, W, Sun, Q. A high-fat diet: an unexpected role in preventing the metastatic seeding of colorectal cancer. Signal Transduction and Targeted Therapy. 2020. 5. doi:10.1038/s41392-020-00386-2. | Study Design
30 | Lopez-Pentecost, M, Crane, TE, Garcia, DO, Role of dietary patterns and acculturation in cancer risk and mortality among postmenopausal Hispanic women: results from the Women’s Health Initiative (WHI). Journal of Public Health (Germany). 2022. 30:811–822. doi:10.1007/s10389-020-01342-8. | Outcome
31 | Moazzen, S, Cortes-Ibañez, FO, van der Vegt, B, Alizadeh, BZ, de Bock, GH. Diet quality indices and gastrointestinal cancer risk: results from the Lifelines study. Eur J Nutr. 2022. 61:317–327. doi:10.1007/s00394-021-02648-3.34338867 | Outcome
32 | Myneni, AA, Giovino, GA, Millen, AE, Indices of Diet Quality and Risk of Lung Cancer in the Women's Health Initiative Observational Study. J Nutr. 2021. 151:1618–1627. doi:10.1093/jn/nxab033 .33982106 | Outcome
33 | Nepal, S, Aslani, Z, Shi, N, Associations of Dietary Patterns with Colorectal Adenomas in the Prostate, Lung, Colorectal, and Ovarian Cancer Cohort. Cancer Epidemiol Biomarkers Prev. 2023. 32(9):1260-1264. doi:10.1158/1055-9965.EPI-23-0143.37327041 | Outcome
34 | Nguyen, LH, Cao, Y, Hur, J, The Sulfur Microbial Diet Is Associated With Increased Risk of Early-Onset Colorectal Cancer Precursors. Gastroenterology. 2021. 161:1423–1432.e4. doi:10.1053/j.gastro.2021.07.008 .34273347 | Outcome
35 | Nguyen, S, Li, H, Yu, D, Adherence to dietary recommendations and colorectal cancer risk: results from two prospective cohort studies. Int J Epidemiol. 2020. 49:270–280. doi: 10.1093/ije/dyz118.31203367 | Outcome
36 | O’Hearn, M, Erndt-Marino, J, Gerber, S, Validation of Food Compass with a healthy diet, cardiometabolic health, and mortality among U.S. adults, 1999–2018. Nat Commun. 2022. 13(1):7066. doi:10.1038/s41467-022-34195-8.36414619 | Study Design
37 | Pan, K, Aragaki, AK, Neuhouser, ML, Low-fat dietary pattern and breast cancer mortality by metabolic syndrome components: a secondary analysis of the Women's Health Initiative (WHI) randomised trial. Br J Cancer. 2021. 125:372–379. doi:10.1038/s41416-021-01379-w .34006923 | Outcome
38 | Park, SY, Boushey, CJ, Shvetsov, YB, Diet Quality and Risk of Lung Cancer in the Multiethnic Cohort Study. Nutrients. 2021. 13. doi:10.3390/nu13051614 . | Outcome
39 | Park, YM, Shivappa, N, Petimar, J, Dietary inflammatory potential, oxidative balance score, and risk of breast cancer: Findings from the Sister Study. Int J Cancer. 2021. 149:615–626. doi: 10.1002/ijc.33581 .33783833 | Intervention/Exposure; Outcome
40 | Peila, R, Chlebowski, R, Manson, JA, Low-fat dietary modification and risk of ductal carcinoma in situ of the breast in the women's health initiative dietary modification trial. Cancer Epidemiology Biomarkers and Prevention. 2021.30:1753–1756. doi: 10.1158/1055-9965.EPI-21-0404 . | Outcome
41 | Peila, R, Lane, DS, Shadyab, AH, Healthy lifestyle index and the risk of ductal carcinoma in situ of the breast in the Women's Health Initiative. Int J Cancer. 2022. 151:526–538. doi: 10.1002/ijc.34034 .35429338 | Intervention/Exposure; Outcome
42 | Plym, A, Zhang, Y, Stopsack, KH, A Healthy Lifestyle in Men at Increased Genetic Risk for Prostate Cancer. Eur Urol. 2022. doi: 10.1016/j.eururo.2022.05.008 . | Intervention/Exposure
43 | Rassy, N, Van Straaten, A, Carette, C, Association of Healthy Lifestyle Factors and Obesity-Related Diseases in Adults in the UK. JAMA Network Open. 2023. 6:E2314741.37234008 | Intervention/Exposure
44 | Ren, X, Yu, C, Peng, L, Compliance with the EAT-Lancet diet and risk of colorectal cancer: a prospective cohort study in 98,415 American adults. Front Nutr. 2023. 10:1264178. doi:10.3389/fnut.2023.1264178.37927505 | Outcome
45 | Schulpen, M, van den Brandt, PA. Mediterranean diet adherence and risk of colorectal cancer: the prospective Netherlands Cohort Study. Eur J Epidemiol. 2020. 35:25–35. doi:10.1007/s10654-019-00549-8.31494792 | Outcome
46 | Sciacca S, Lo Giudice A, Asmundo MG, Cimino S, Morgia G, Alshatwi AA, Adherence to Healthy or Unhealthy Pro-Vegetarian Plant-Based Diets Have Different Impact on Prostate Cancer Severity: Preliminary Findings. Nutr Cancer. 2024. 76(1):98–105. doi:10.1080/01635581.2023.2279240 37941310 | Study Design; Outcome
47 | Shin, S, Saito, E, Sawada, N, Dietary patterns and colorectal cancer risk in middle-aged adults: A large population-based prospective cohort study. Clin Nutr. 2018. 37(3):1019-1026. doi:10.1016/j.clnu.2017.04.015.28526274 | Publication Date
48 | Shin, S, Saito, E, Sawada, N, Dietary patterns and prostate cancer risk in Japanese: the Japan Public Health Center-based Prospective Study (JPHC Study). Cancer Causes and Control. 2018. 29(6):589-600. doi:10.1007/s10552-018-1030-3.29671180 | Outcome
49 | Sieri, S, Agnoli, C, Pala, V, Dietary Intakes of Animal and Plant Proteins and Risk of Colorectal Cancer: The EPIC-ltaly Cohort. Cancers (Basel). 2022. 14. doi:10.3390/cancers14122917 . | Intervention/Exposure
50 | Thordardottir, GS, Einarsdottir, K, Thordardottir, M, Dietary patterns in adolescence and risk of colorectal cancer: a population-based study. Cancer Causes Control. 2022. 33:205–211. doi:10.1007/s10552-021-01524-z .34800195 | Intervention/Exposure; Age: Intervention/Exposure
51 | Ugai, T, Liu, L, Tabung, FK, Prognostic role of inflammatory diets in colorectal cancer overall and in strata of tumor-infiltrating lymphocyte levels. Clin Transl Med. 2022. 12(11):e1114. doi:10.1002/ctm2.1114.36437503 | Health Status
52 | Vitellius, C, Bertrais, S, Antier, J, Evaluation of a risk score based on dietary and lifestyle factors to target a population at risk in colorectal cancer screening. Digestive and Liver Disease. 2021. 53:900–907. doi: 10.1016/j.dld.2021.03.008 .33926818 | Study Design; Intervention/Exposure
53 | Wang, F, Ugai, T, Haruki, K, Healthy and unhealthy plant-based diets in relation to the incidence of colorectal cancer overall and by molecular subtypes. Clin Transl Med. 2022. 12:e893. doi:10.1002/ctm2.893.35998061 | Outcome
54 | Wang, L, Du, M, Wang, K, Association of ultra-processed food consumption with colorectal cancer risk among men and women: Results from three prospective US cohort studies. The BMJ. 2022. doi:10.1136/bmj-2021-068921. | Outcome
55 | Wang P, Song M, Eliassen AH, Wang M, Giovannucci EL. Dietary patterns and risk of colorectal cancer: a comparative analysis. Int J Epidemiol. 2023. 52(1):96-106. doi:10.1093/ije/dyac230.36515537 | Outcome
56 | Wang, Q, Hashemian, M, Sepanlou, SG, Dietary quality using four dietary indices and lung cancer risk: the Golestan Cohort Study (GCS). Cancer Causes Control. 2021.32:493–503. doi: 10.1007/s10552-021-01400-w .33611724 | Outcome
57 | Wang, W, Fung, TT, Wang, M, Association of the Insulinemic Potential of Diet and Lifestyle With Risk of Digestive System Cancers in Men and Women. JNCI Cancer Spectrum. 2018. 2(4):pky080. doi:10.1093/jncics/pky080.30740588 | Intervention/Exposure
58 | Wang, Y, Nguyen, LH, Mehta, RS, Association Between the Sulfur Microbial Diet and Risk of Colorectal Cancer. JAMA Netw Open. 2021. 4:e2134308. doi:10.1001/jamanetworkopen.2021.34308 .34767023 | Intervention/Exposure
59 | Watling, CZ, Schmidt, JA, Dunneram, Y, Risk of cancer in regular and low meat-eaters, fish-eaters, and vegetarians: a prospective analysis of UK Biobank participants. BMC Med. 2022. 20:73. doi:10.1186/s12916-022-02256-w .35197066 | Intervention/Exposure
60 | Wei, X, Zhu, C, Ji, M, Diet and Risk of Incident Lung Cancer: A Large Prospective Cohort Study in UK Biobank. Am J Clin Nutr. 2021. 114:2043–2051. doi: 10.1093/ajcn/nqab298 .34582556 | Outcome
61 | Xiao, Y, He, H, Xiang, L, Gu, H, Xu, Z, Luo, H, Association between sulfur microbial diet and the risk of colorectal cancer precursors in older adults. Front Nutr. 2023. 10:1167372. doi:10.3389/fnut.2023.1167372.37645627 | Outcome
62 | Xiao, Y, Wang, Y, Gu, H, Adherence to the Paleolithic diet and Paleolithic-like lifestyle reduce the risk of colorectal cancer in the United States: a prospective cohort study. J Transl Med. 2023. 21(1):482. doi:10.1186/s12967-023-04352-8.37468920 | Outcome
63 | Yue, Y, Hur, J, Cao, Y, Prospective evaluation of dietary and lifestyle pattern indices with risk of colorectal cancer in a cohort of younger women. Ann Oncol. 2021.32:778–786. doi:10.1016/j.annonc.2021.03.200.33812017 | Outcome
64 | Yu YC, Paragomi P, Jin A, Wang R, Schoen RE, Koh WP, Low-Carbohydrate Diet Score and the Risk of Colorectal Cancer: Findings from the Singapore Chinese Health Study. Cancer Epi Biom Prev. 2023.32(6):802-808.doi:10.1158/1055-9965.EPI-22-0683 | Intervention/Exposure
65 | Zhang, J, Nyvang, D, Ibsen, DB, Adherence to the Danish food-based dietary guidelines and risk of colorectal cancer: a cohort study. Br J Cancer. 2021. 125:1726–1733. doi:10.1038/s41416-021-01556-x.34593992 | Outcome
66 | Zhang, J, Yu, H, Huang, T, Importance of ideal cardiovascular health metrics in the risk of colorectal cancer among people aged 50 years or older: a UK Biobank cohort study. BMJ Open. 2022. 12:e059642. doi:10.1136/bmjopen-2021-059642 . | Comparator
67 | Zhang, Y, Zhong, G, Zhu, M, Association Between Diabetes Risk Reduction Diet and Lung Cancer Risk in 98,159 Participants: Results From a Prospective Study. Front Oncol. 2022. 12:855101. doi:10.3389/fonc.2022.855101 .35574372 | Outcome
68 | Zhang, YB, Pan, XF, Lu, Q, Associations of combined healthy lifestyles with cancer morbidity and mortality among individuals with diabetes: results from five cohort studies in the USA, the UK and China. Diabetologia. 2022. doi:10.1007/s00125-022-05754-x . | Intervention/Exposure; Health Status
69 | Zhang, Z, Tabung, FK, Jin, Q, Diet-Driven Inflammation and Insulinemia and Risk of Interval Breast Cancer. Nutr Cancer. 2022. 74:3179–3193. doi:10.1080/01635581.2022.2063350 .35471124 | Outcome