# Appendix 2 Conclusion statements from the existing systematic reviews for the research question: What is the relationship between dietary patterns consumption and risk of breast cancer?

Table A 2 Inclusion and exclusion criteria comparison between existing^*^ * Boushey C, Ard J, Bazzano L, Heymsfield S, Mayer-Davis E, Sabaté J, Snetselaar L, Van Horn L, Schneeman B, English LK, Bates M, Callahan E, Butera G, Terry N, Obbagy J. Dietary Patterns and Breast, Colorectal, Lung, and Prostate Cancer: A Systematic Review. July 2020. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: 10.52570/NESR.DGAC2020.SR0104 and updated systematic reviews for the research question: What is the relationship between dietary patterns and risk of breast cancer?

Citation | Conclusion statement and grade
2015 Dietary Guidelines Advisory Committee: Systematic Reviews of the Dietary Patterns, Foods and Nutrients, and Health Outcomes Subcommittee. February 2015. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: https://nesr.usda.gov/sites/default/files/2019-04/2015DGAC-SR-DietaryPatterns.pdf | Moderate evidence indicates that dietary patterns rich in vegetables, fruit and whole grains, and lower in animal products and refined carbohydrate, are associated with reduced risk of postmenopausal breast cancer. The data regarding this dietary pattern and premenopausal breast cancer risk point in the same direction, but the evidence is limited due to fewer studies.; (Grade: Moderate, postmenopausal; Limited, premenopausal)
Boushey C, Ard J, Bazzano L, Heymsfield S, Mayer-Davis E, Sabaté J, Snetselaar L, Van Horn L, Schneeman B, English LK, Bates M, Callahan E, Butera G, Terry N, Obbagy J. Dietary Patterns and Breast, Colorectal, Lung, and Prostate Cancer: A Systematic Review. July 2020. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: 10.52570/NESR.DGAC2020.SR0104 | Moderate evidence indicates that dietary patterns rich in vegetables, fruits, and whole grains, and lower in animal-source foods and refined carbohydrates, are associated with reduced risk of postmenopausal breast cancer. The data regarding these dietary patterns and premenopausal breast cancer risk point in the same direction, but the evidence is limited as fewer studies include premenopausal breast cancer. (Grade: Moderate - Postmenopausal breast cancer risk, Limited – Premenopausal breast cancer risk)