# Appendix 1 Abbreviations

Table A 1 List of abbreviations
Abbreviation: Full name
DP: Dietary Pattern
ER: Estrogen-receptor
FFQ: Food frequency questionnaire
HDI: Human Development Index
HEI: Healthy Eating Index
HER2: Human epidermal growth factor
HHS: United States Department of Health and Human Services
NCC: Nested case-control study
NESR: Nutrition Evidence Systematic Review
PCS: Prospective cohort study
PR: Progesterone-receptor
RCT: Randomized controlled trial
SEP: Socioeconomic position
USDA: United States Department of Agriculture