# References of included articles in the systematic review

1 Barnes LL, Dhana K, Liu X, Trial of the MIND Diet for Prevention of Cognitive Decline in Older Persons. N Engl J Med. Aug 17 2023;389(7):602–611. doi:10.1056/NEJMoa2302368. Epub 2023 Jul 18.37466280
2 Wagner M, Grodstein F, Proust-Lima C, Samieri C. Long-Term Trajectories of Body Weight, Diet, and Physical Activity From Midlife Through Late Life and Subsequent Cognitive Decline in Women. Am J Epidemiol. Apr 2 2020;189(4):305–313. doi:10.1093/aje/kwz262 31781745
3 Agarwal P, Dhana K, Barnes LL, Unhealthy foods may attenuate the beneficial relation of a Mediterranean diet to cognitive decline. Alzheimers Dement. Jul 2021;17(7):1157–1165. doi:10.1002/alz.12277. Epub 2021 Jan 7.33410584
4 Andreu-Reinon ME, Chirlaque MD, Gavrila D, Mediterranean Diet and Risk of Dementia and Alzheimer's Disease in the EPIC-Spain Dementia Cohort Study. Nutrients. Feb 22 2021;13(2)doi:10.3390/nu13020700
5 Ashby-Mitchell K, Peeters A, Anstey KJ. Role of dietary pattern analysis in determining cognitive status in elderly Australian adults. Nutrients. Feb 4 2015;7(2):1052–67. doi:10.3390/nu7021052 25658241
6 Beydoun MA, Weiss J, Beydoun HA, Pathways explaining racial/ethnic disparities in incident all-cause and Alzheimer's disease dementia among older US men and women. Alzheimers Dement (N Y). 2022;8(1):e12275. doi:10.1002/trc2.12275 35317081
7 Boumenna T, Scott TM, Lee JS, MIND Diet and Cognitive Function in Puerto Rican Older Adults. J Gerontol A Biol Sci Med Sci. Mar 3 2022;77(3):605–613. doi:10.1093/gerona/glab261 34551094
8 Charisis S, Ntanasi E, Yannakoulia M, Mediterranean diet and risk for dementia and cognitive decline in a Mediterranean population. J Am Geriatr Soc. Jun 2021;69(6):1548–1559. doi:10.1111/jgs.17072. Epub 2021 Mar 16.33724444
9 Chen H, Dhana K, Huang Y, Association of the Mediterranean Dietary Approaches to Stop Hypertension Intervention for Neurodegenerative Delay (MIND) Diet With the Risk of Dementia. JAMA Psychiatry. Jun 1 2023;80(6):630–638. doi:10.1001/jamapsychiatry.2023.0800 37133875
10 Chen J, Wu F, Magnussen CG, Dietary patterns from youth to adulthood and cognitive function in midlife: The cardiovascular risk in Young Finns Study. Nutrition. Aug 2023;112:112063. doi:10.1016/j.nut.2023.112063 37269718
11 Chen LW, Chou YC, Lee MS, Chiou JM, Chen JH, Chen YC. Longitudinal trajectories of dietary quality and cognitive performance in older adults: Results from a 6-year cohort study. Clin Nutr. Jun 2023;42(6):879–886. doi:10.1016/j.clnu.2023.04.002. Epub 2023 Apr 7.37086616
12 Chen X, Liu Z, Sachdev PS, Kochan NA, Brodaty H, OĽeary F. Association of adherence to the Australian Dietary Guidelines with cognitive performance and cognitive decline in the Sydney Memory and Ageing Study: a longitudinal analysis. J Nutr Sci. 2021;10:e86. doi:10.1017/jns.2021.44 34733498
13 Chen X, Liu Z, Sachdev PS, Kochan NA, OĽeary F, Brodaty H. Association of Dietary Patterns with Cognitive Function and Cognitive Decline in Sydney Memory and Ageing Study: A Longitudinal Analysis. J Acad Nutr Diet. May 2022;122(5):949–960.e15. doi:10.1016/j.jand.2021.10.018. Epub 2021 Oct 22.34688967
14 Chen YC, Jung CC, Chen JH, Association of Dietary Patterns With Global and Domain-Specific Cognitive Decline in Chinese Elderly. J Am Geriatr Soc. Jun 2017;65(6):1159–1167. doi:10.1111/jgs.14741. Epub 2017 Jan 16.28092399
15 Chou YC, Lee MS, Chiou JM, Chen TF, Chen YC, Chen JH. Association of Diet Quality and Vegetable Variety with the Risk of Cognitive Decline in Chinese Older Adults. Nutrients. Jul 20 2019;11(7)doi:10.3390/nu11071666
16 Corley J, Deary IJ. Dietary patterns and trajectories of global- and domain-specific cognitive decline in the Lothian Birth Cohort 1936. Br J Nutr. Oct 28 2021;126(8):1237–1246. doi:10.1017/S0007114520005139. Epub 2020 Dec 23.33355060
17 Cornelis MC, Agarwal P, Holland TM, van Dam RM. MIND Dietary Pattern and Its Association with Cognition and Incident Dementia in the UK Biobank. Nutrients. Dec 21 2022;15(1)doi:10.3390/nu15010032
18 D'Amico D, Parrott MD, Greenwood CE, Sex differences in the relationship between dietary pattern adherence and cognitive function among older adults: findings from the NuAge study. Nutr J. Jun 20 2020;19(1):58. doi:10.1186/s12937-020-00575-3 32563260
19 Daniel GD, Chen H, Bertoni AG, DASH diet adherence and cognitive function: Multi-ethnic study of atherosclerosis. Clin Nutr ESPEN. Dec 2021;46:223–231. doi:10.1016/j.clnesp.2021.10.004. Epub 2021 Oct 11.34857201
20 de Crom TOE, Mooldijk SS, Ikram MK, Ikram MA, Voortman T. MIND diet and the risk of dementia: a population-based study. Alzheimers Res Ther. Jan 12 2022;14(1):8. doi:10.1186/s13195-022-00957-1 35022067
21 de Crom TOE, Steur M, Ikram MK, Ikram MA, Voortman T. Plant-based dietary patterns and the risk of dementia: a population-based study. Age Ageing. Sep 1 2023;52(9)doi:10.1093/ageing/afad178
22 Dhana K, James BD, Agarwal P, MIND Diet, Common Brain Pathologies, and Cognition in Community-Dwelling Older Adults. J Alzheimers Dis. 2021;83(2):683–692. doi:10.3233/JAD-210107.34334393
23 Flores AC, Jensen GL, Mitchell DC, Prospective Study of Diet Quality and the Risk of Dementia in the Oldest Old. Nutrients. Mar 4 2023;15(5)doi:10.3390/nu15051282
24 Galbete C, Toledo E, Toledo JB, Mediterranean diet and cognitive function: the SUN project. J Nutr Health Aging. Mar 2015;19(3):305–12. doi:10.1007/s12603-015-0441-z.25732216
25 Gelber RP, Petrovitch H, Masaki KH, Lifestyle and the risk of dementia in Japanese-american men. J Am Geriatr Soc. Jan 2012;60(1):118–23. doi:10.1111/j.1532-5415.2011.03768.x. Epub 2011 Dec 28.22211390
26 Glans I, Sonestedt E, Nagga K, Association Between Dietary Habits in Midlife With Dementia Incidence Over a 20-Year Period. Neurology. Jan 3 2023;100(1):e28–e37. doi:10.1212/WNL.0000000000201336 36224029
27 Granic A, Davies K, Adamson A, Dietary Patterns High in Red Meat, Potato, Gravy, and Butter Are Associated with Poor Cognitive Functioning but Not with Rate of Cognitive Decline in Very Old Adults. J Nutr. Feb 2016;146(2):265–74. doi:10.3945/jn.115.216952 26740685
28 Gregory S, Ritchie CW, Ritchie K, Shannon O, Stevenson EJ, Muniz-Terrera G. Mediterranean diet score is associated with greater allocentric processing in the EPAD LCS cohort: A comparative analysis by biogeographical region. Front Aging. 2022;3:1012598. doi:10.3389/fragi.2022.1012598 36568511
29 Guo J, Brickman AM, Manly JJ, Association of Life's Simple 7 with incident dementia and its modification by the apolipoprotein E genotype. Alzheimers Dement. Dec 2021;17(12):1905–1913. doi:10.1002/alz.12359. Epub 2021 May 2.33938146
30 Hsiao FY, Peng LN, Lee WJ, Chen LK. Higher dietary diversity and better healthy aging: A 4-year study of community-dwelling middle-aged and older adults from the Taiwan Longitudinal Study of Aging. Exp Gerontol. Oct 15 2022;168:111929. doi:10.1016/j.exger.2022.111929. Epub 2022 Aug 14.35977645
31 Hu EA, Wu A, Dearborn JL, Adherence to Dietary Patterns and Risk of Incident Dementia: Findings from the Atherosclerosis Risk in Communities Study. J Alzheimers Dis. 2020;78(2):827–835. doi:10.3233/JAD-200392.33044177
32 Jia X, Su C, Du W, Association of Dietary Quality with Cognitive Function in Chinese Adults Aged 55 Years and Above: A Longitudinal Study. J Nutr Health Aging. 2023;27(7):514–523. doi:10.1007/s12603-023-1941-x.37498099
33 Keenan TD, Agron E, Mares JA, Adherence to a Mediterranean diet and cognitive function in the Age-Related Eye Disease Studies 1 & 2. Alzheimers Dement. Jun 2020;16(6):831–842. doi:10.1002/alz.12077 32285590
34 Kjeldsen EW, Thomassen JQ, Rasmussen KL, Nordestgaard BG, Tybjaerg-Hansen A, Frikke-Schmidt R. Adherence to dietary guidelines and risk of dementia: a prospective cohort study of 94 184 individuals. Epidemiol Psychiatr Sci. Oct 10 2022;31:e71. doi:10.1017/S2045796022000567 36214322
35 Lai JS, Cheng GH, Chong YS, Chong MF, Koh WP. Longitudinal Dietary Trajectories With Cognitive and Psychosocial Well-Being in Chinese Adults Aged 85 Years and Older in Singapore. Innov Aging. 2023;7(4):igad036. doi:10.1093/geroni/igad036 37228450
36 Larsson SC, Wolk A. The Role of Lifestyle Factors and Sleep Duration for Late-Onset Dementia: A Cohort Study. J Alzheimers Dis. 2018;66(2):579–586. doi:10.3233/JAD-180529 30320581
37 Liang F, Fu J, Turner-McGrievy G, Association of Body Mass Index and Plant-Based Diet with Cognitive Impairment among Older Chinese Adults: A Prospective, Nationwide Cohort Study. Nutrients. Jul 29 2022;14(15)doi:10.3390/nu14153132
38 Liu X, Dhana K, Barnes LL, A healthy plant-based diet was associated with slower cognitive decline in African American older adults: a biracial community-based cohort. Am J Clin Nutr. Oct 6 2022;116(4):875–886. doi:10.1093/ajcn/nqac204.35906190
39 Lohman MC, Wei J, Bawa EM, Fallahi A, Verma M, Merchant AT. Longitudinal Associations of Diet, Food Insecurity, and Supplemental Nutrition Assistance Program Use with Global Cognitive Performance in Middle-Aged and Older Adults. J Nutr. Feb 2024;154(2):714–721. doi:10.1016/j.tjnut.2023.12.042 38158186
40 Lu Y, Matsuyama S, Sugawara Y, Sone T, Tsuji I. Changes in a specific dietary pattern and incident dementia: A prospective cohort study. Clin Nutr. May 2021;40(5):3495–3502. doi:10.1016/j.clnu.2020.11.036. Epub 2020 Dec 5.33342602
41 Malek Rivan NF, Shahar S, Fakhruddin N, You YX, Che Din N, Rajikan R. The effect of dietary patterns on mild cognitive impairment and dementia incidence among community-dwelling older adults. Front Nutr. 2022;9:901750. doi:10.3389/fnut.2022.901750 36003836
42 Mamalaki E, Charisis S, Mourtzi N, Genetic risk for Alzheimer's disease and adherence to the Mediterranean diet: results from the HELIAD study. Nutr Neurosci. Mar 2024;27(3):289–299. doi:10.1080/1028415X.2023.2187952 36961750
43 Mattei J, Bigornia SJ, Sotos-Prieto M, Scott T, Gao X, Tucker KL. The Mediterranean Diet and 2-Year Change in Cognitive Function by Status of Type 2 Diabetes and Glycemic Control. Diabetes Care. Aug 2019;42(8):1372–1379. doi:10.2337/dc19-0130. Epub 2019 May 23.31123154
44 Melo van Lent D, O'Donnell A, Beiser AS, Mind Diet Adherence and Cognitive Performance in the Framingham Heart Study. J Alzheimers Dis. 2021;82(2):827–839. doi:10.3233/JAD-201238.34092629
45 Melo van Lent D, Samieri C, Grodstein F, Seshadri S. Empirical Dietary Inflammatory Pattern Scores Are Not Associated with Worse Cognitive Performance in the Nurses' Health Study. J Nutr. Nov 2022;152(11):2526–2533. doi:10.1093/jn/nxac157. Epub 2022 Jul 26.36774118
46 Milte CM, Ball K, Crawford D, McNaughton SA. Diet quality and cognitive function in mid-aged and older men and women. BMC Geriatr. Dec 21 2019;19(1):361. doi:10.1186/s12877-019-1326-5 31864295
47 Morris MC, Tangney CC, Wang Y, MIND diet slows cognitive decline with aging. Alzheimers Dement. Sep 2015;11(9):1015–22. doi:10.1016/j.jalz.2015.04.011. Epub 2015 Jun 15.26086182
48 Morris MC, Tangney CC, Wang Y, Sacks FM, Bennett DA, Aggarwal NT. MIND diet associated with reduced incidence of Alzheimer's disease. Alzheimers Dement. Sep 2015;11(9):1007–14. doi:10.1016/j.jalz.2014.11.009. Epub 2015 Feb 11.25681666
49 Moustafa B, Trifan G, Isasi CR, Association of Mediterranean Diet With Cognitive Decline Among Diverse Hispanic or Latino Adults From the Hispanic Community Health Study/Study of Latinos. JAMA Netw Open. Jul 1 2022;5(7):e2221982. doi:10.1001/jamanetworkopen.2022.21982 35834250
50 Mueller KD, Norton D, Koscik RL, Self-reported health behaviors and longitudinal cognitive performance in late middle age: Results from the Wisconsin Registry for Alzheimer's Prevention. PLoS One. 2020;15(4):e0221985. doi:10.1371/journal.pone.0221985 32324741
51 Munoz-Garcia MI, Martinez-Gonzalez MA, Razquin C, Fernandez-Matarrubia M, Guillen-Grima F, Toledo E. Exploratory dietary patterns and cognitive function in the "Seguimiento Universidad de Navarra" (SUN) Prospective Cohort. Eur J Clin Nutr. Jan 2022;76(1):48–55. doi:10.1038/s41430-021-00922-5 33986490
52 Munoz-Garcia MI, Toledo E, Razquin C, "A priori" Dietary Patterns and Cognitive Function in the SUN Project. Neuroepidemiology. 2020;54(1):45–57. doi:10.1159/000502608. Epub 2019 Oct 10.31600758
53 Nicoli C, Galbussera AA, Bosetti C, The role of diet on the risk of dementia in the oldest old: The Monzino 80-plus population-based study. Clin Nutr. Jul 2021;40(7):4783–4791. doi:10.1016/j.clnu.2021.06.016. Epub 2021 Jun 18.34242918
54 Nishi SK, Babio N, Gomez-Martinez C, Mediterranean, DASH, and MIND Dietary Patterns and Cognitive Function: The 2-Year Longitudinal Changes in an Older Spanish Cohort. Front Aging Neurosci. 2021;13:782067. doi:10.3389/fnagi.2021.782067 34966270
55 Nooyens ACJ, Yildiz B, Hendriks LG, Adherence to dietary guidelines and cognitive decline from middle age: the Doetinchem Cohort Study. Am J Clin Nutr. Sep 1 2021;114(3):871–881. doi:10.1093/ajcn/nqab109 34004676
56 Olsson E, Karlstrom B, Kilander L, Byberg L, Cederholm T, Sjogren P. Dietary patterns and cognitive dysfunction in a 12-year follow-up study of 70 year old men. J Alzheimers Dis. 2015;43(1):109–19. doi:10.3233/JAD-140867 25062901
57 Parrott MD, Carmichael PH, Laurin D, The Association Between Dietary Pattern Adherence, Cognitive Stimulating Lifestyle, and Cognitive Function Among Older Adults From the Quebec Longitudinal Study on Nutrition and Successful Aging. J Gerontol B Psychol Sci Soc Sci. Feb 17 2021;76(3):444–450. doi:10.1093/geronb/gbaa178.33063101
58 Razquin C, Menendez-Acebal C, Cervantes S, Hypertension and changes in cognitive function in a Mediterranean population. Nutr Neurosci. Mar 2022;25(3):612–620. doi:10.1080/1028415X.2020.1788773 32635835
59 Rodrigues B, Coelho A, Portugal-Nunes C, Higher Adherence to the Mediterranean Diet Is Associated With Preserved White Matter Integrity and Altered Structural Connectivity. Front Neurosci. 2020;14:786. doi:10.3389/fnins.2020.00786 32903442
60 Samuelsson J, Najar J, Wallengren O, Interactions between dietary patterns and genetic factors in relation to incident dementia among 70-year-olds. Eur J Nutr. Mar 2022;61(2):871–884. doi:10.1007/s00394-021-02688-9 34632537
61 Shang X, Hodge AM, Hill E, Zhu Z, He M. Associations of Dietary Pattern and Sleep Duration with Cognitive Decline in Community-Dwelling Older Adults: A Seven-Year Follow-Up Cohort Study. J Alzheimers Dis. 2021;82(4):1559–1571. doi:10.3233/JAD-201329.34180411
62 Shannon OM, Ranson JM, Gregory S, Mediterranean diet adherence is associated with lower dementia risk, independent of genetic predisposition: findings from the UK Biobank prospective cohort study. BMC Med. Mar 14 2023;21(1):81. doi:10.1186/s12916-023-02772-3 36915130
63 Tanaka T, Talegawkar SA, Jin Y, Colpo M, Ferrucci L, Bandinelli S. Adherence to a Mediterranean Diet Protects from Cognitive Decline in the Invecchiare in Chianti Study of Aging. Nutrients. Dec 19 2018;10(12)doi:10.3390/nu10122007
64 Tangney CC, Li H, Wang Y, Relation of DASH- and Mediterranean-like dietary patterns to cognitive decline in older persons. Neurology. Oct 14 2014;83(16):1410–6. doi:10.1212/WNL.0000000000000884. Epub 2014 Sep 17.25230996
65 Thomas A, Ryan CP, Caspi A, Diet, Pace of Biological Aging, and Risk of Dementia in the Framingham Heart Study. Ann Neurol. Jun 2024;95(6):1069–1079. doi:10.1002/ana.26900 38407506
66 Tong EH, Lai JS, Whitton C, Changes in Diet Quality from Mid- to Late Life Are Associated with Cognitive Impairment in the Singapore Chinese Health Study. J Nutr. Sep 4 2021;151(9):2800–2807. doi:10.1093/jn/nxab179.34049404
67 Trichopoulou A, Kyrozis A, Rossi M, Mediterranean diet and cognitive decline over time in an elderly Mediterranean population. Eur J Nutr. Dec 2015;54(8):1311–21. doi:10.1007/s00394-014-0811-z. Epub 2014 Dec 9.25482573
68 van Soest APM, van de Rest O, Witkamp RF, van der Velde N, de Groot L. The association between adherence to a plant-based diet and cognitive ageing. Eur J Nutr. Aug 2023;62(5):2053–2062. doi:10.1007/s00394-023-03130-y 36905458
69 Vercambre MN, Grodstein F, Berr C, Kang JH. Mediterranean diet and cognitive decline in women with cardiovascular disease or risk factors. J Acad Nutr Diet. Jun 2012;112(6):816–23. doi:10.1016/j.jand.2012.02.023.22709809
70 Vlachos GS, Yannakoulia M, Anastasiou CA, The role of Mediterranean diet in the course of subjective cognitive decline in the elderly population of Greece: results from a prospective cohort study. Br J Nutr. Dec 14 2022;128(11):2219–2229. doi:10.1017/S0007114521005109. Epub 2021 Dec 23.34937581
71 Vu THT, Beck T, Bennett DA, Adherence to MIND Diet, Genetic Susceptibility, and Incident Dementia in Three US Cohorts. Nutrients. Jul 3 2022;14(13)doi:10.3390/nu14132759
72 Wade AT, Elias MF, Murphy KJ. Adherence to a Mediterranean diet is associated with cognitive function in an older non-Mediterranean sample: findings from the Maine-Syracuse Longitudinal Study. Nutr Neurosci. Jul 2021;24(7):542–553. doi:10.1080/1028415X.2019.1655201. Epub 2019 Aug 21.31432770
73 Wagner M, Agarwal P, Leurgans SE, The association of MIND diet with cognitive resilience to neuropathologies. Alzheimers Dement. Aug 2023;19(8):3644–3653. doi:10.1002/alz.12982. Epub 2023 Feb 28.36855023
74 Wang Z, Pang Y, Liu J, Wang J, Xie Z, Huang T. Association of healthy lifestyle with cognitive function among Chinese older adults. Eur J Clin Nutr. Feb 2021;75(2):325–334. doi:10.1038/s41430-020-00785-2. Epub 2020 Oct 28.33116235
75 Wu H, Gu Y, Meng G, Quality of plant-based diet and the risk of dementia and depression among middle-aged and older population. Age Ageing. May 1 2023;52(5)doi:10.1093/ageing/afad070.
76 Yuan C, Cao Y, Ascherio A, Long-term diet quality and its change in relation to late-life subjective cognitive decline. Am J Clin Nutr. Jan 11 2022;115(1):232–243. doi:10.1093/ajcn/nqab326.34562097
77 Zhang J, Cao X, Li X, Associations of Midlife Dietary Patterns with Incident Dementia and Brain Structure: Findings from the UK Biobank Study. Am J Clin Nutr. Jul 2023;118(1):218–227. doi:10.1016/j.ajcnut.2023.05.007 37150507
78 Zhang JJ, Ye YX, Dorajoo R, APOE genotype modifies the association between midlife adherence to the planetary healthy diet and cognitive function in later life among Chinese adults in Singapore. The Journal of nutrition. Nov 2023 2023;doi:10.1016/j.tjnut.2023.11.024
79 Zhang S, Otsuka R, Nishita Y, Twenty-year prospective cohort study of the association between a Japanese dietary pattern and incident dementia: the NILS-LSA project. Eur J Nutr. Jun 2023;62(4):1719–1729. doi:10.1007/s00394-023-03107-x 36808562
80 Zhang X, Huang F, Zhang J, Association between Micronutrient-Related Dietary Pattern and Cognitive Function among Persons 55 Years and Older in China: A Longitudinal Study. Article. Nutrients. 2023;15(3)
81 Zhang X, Wang Y, Liu W, Diet quality, gut microbiota, and microRNAs associated with mild cognitive impairment in middle-aged and elderly Chinese population. Am J Clin Nutr. Aug 2 2021;114(2):429–440. doi:10.1093/ajcn/nqab078.33871591
82 Zhou YF, Song XY, Wu J, Association Between Dietary Patterns in Midlife and Healthy Ageing in Chinese Adults: The Singapore Chinese Health Study. J Am Med Dir Assoc. Jun 2021;22(6):1279–1286. doi:10.1016/j.jamda.2020.09.045. Epub 2020 Nov 18.33218913
83 Zhu A, Yuan C, Pretty J, Ji JS. Plant-based dietary patterns and cognitive function: A prospective cohort analysis of elderly individuals in China (2008–2018). Brain Behav. Aug 2022;12(8):e2670. doi:10.1002/brb3.2670 35833240