# Results

## Literature search and screening results

The literature search (Appendix 3) yielded 8,807 search results after the removal of duplicates (see Figure 2). Dual-screening resulted in the exclusion of 7,746 titles, 704 abstracts, and 276 full-texts articles. Reasons for full-text exclusion are in Appendix 5. Two additional articles were identified from the manual search. The body of evidence included 83 articles.

Figure 2 Literature search and screen flowchart

## Description of the evidence

Eighty-three articles met inclusion criteria examining the relationship between dietary patterns consumed and risk of cognitive decline, dementia, Alzheimer’s disease, and/or mild cognitive impairment (see Table 6). Included articles were published between January 2012 and February 2024 and came from the following study designs: 1 article from a randomized controlled trial^1^ (RCT) and 82 articles from observational studies (1 nested case-control study,^2^ and 81 prospective cohort studies^3–83^).

### Population

Analytic sample size of study group of the 1 RCT was N=571.^1^ Among observational studies, sample size of study groups ranged from N=76^59^ up to N=180,532^75^. Follow-up times for the RCT were conducted at 6 months, 1 year, 2 years, and 3 years^1^. Among observational studies, all participants were followed for a mean of at least 1.5 years, but the mean follow-up duration across observational evidence ranged between 18 months/1.5 years up to 31 years. Follow-up duration was not specified in 4 observational studies^22, 32, 38, 71^.

Collectively, studies were conducted in a total of 18 countries. Twenty-nine (n=29) articles were published using data collected in the United States, including 1 RCT,^1^ with the following 19 cohorts represented in the observational data:

- Rush Memory and Aging Project (MAP),^22, 47, 48, 64, 71, 73^ n= 6
- Framingham Heart Study (FHS) Offspring Cohort,^9, 44, 65^ n=3
- Nurses’ Health Study (NHS),^2, 45, 76^ n=3
- Chicago Health and Aging Project,^3, 38, 71^ n=3
- Boston Puerto Rican Health Study (BPRHS),^7, 43^ n=2
- Health and Retirement Study (HRS),^9, 39^ n=2
- National Health and Nutrition Examination Survey (NHANES) II,^6^ n=1
- Multi-Ethnic Study of Atherosclerosis (MESA),^19^ n=1
- Geisinger Rural Aging Study (GRAS),^23^ n=1
- Honolulu-Asia Aging Study (HAAS),^25^ n=1
- Washington Heights-Inwood Columbia Aging Project (WHICAP),^29^ n=1
- Atherosclerosis Risk in Communities (ARIC) Study,^31^ n=1
- Age-Related Eye Disease Studies 2,^33^ n=1
- Hispanic Community Health Study/Study of Latinos (HCHS/SOL),^49^ n=1
- Wisconsin Registry for Alzheimer’s Prevention (WRAP),^50^ n=1
- Women’s Antioxidant Cardiovascular Study (WACS),^69^ n=1
- Women’s Health Initiative Memory Study (WHIMS),^71^ n=1
- Maine-Syracuse Longitudinal Study (MSLS),^72^ n=1
- Whitehall II Study,^9^ n=1

Additional countries and cohorts were represented in the data as follows:

- China, n=7 (China Health and Nutrition Survey (CHNS),^32, 80^ n=2; Chinese Longitudinal Healthy Longevity Survey (CLHS),^37, 61, 74, 83^ n=4; Effects and Mechanism Investigation of Cholesterol and Oxysterol on Alzheimer’s disease (EMCOA) Study,^81^ n=1)
- Spain, n=7 (European Prospective Investigation into Cancer and Nutrition (EPIC) Spain,^4^ n=1; SUN (Seguimiento Universidad de Navarra) Study,^24, 51, 52, 58^ n=4; PREDIMED-Plus secondary analysis,^54^ n=1)
- United Kingdom, n=5 (UK Biobank,^17, 62, 75, 77^ n=4; Newcastle 85+ Study,^27^ n=1)
- Australia, n=4 (Sydney Memory and Ageing Study (MAS),^12, 13^ n=2; Australian Diabetes, Obesity and Lifestyle Study (AusDiab),^5^ n=1; Wellbeing, Eating and Exercise for a Long Life (WELL) study,^46^ n=1)
- Greece, n=4 (Hellenic Longitudinal Investigation of Aging and Diet (HELIAD),^8, 42, 70^ n=3; European Prospective Investigation into Cancer and Nutrition (EPIC) Greece,^67^ n=1)
- Netherlands, n=4 (Rotterdam Study,^20, 21^ n=2; Doetinchem Cohort Study,^55^ n=1; B-Proof trial, Control group only,^68^ n=1)
- Singapore, n=4 (Singapore Chinese Health Study,^35, 66, 78, 82^ n=4)
- Sweden, n=4 (Malmo Diet and Cancer study (MDCS),^26^ n=1; Swedish Infrastructure for Medical Population-based Life-course Environmental Research (SIMPLER),^36^ n=1; Uppsala Longitudinal Study of Adult Men (ULSAM),^56^ n=1; Gothenburg H70 Birth Cohort Studies,^60^ n=1)
- Taiwan, n=4 (Taiwan Initiative for Geriatric Epidemiological Research (TIGER),^11, 15^ n=2; Taiwan Longitudinal Study on Aging (TLSA),^30^ n=1; not reported,^14^ n=1)
- Canada, n=2 (Quebec Longitudinal Study on Nutrition and Successful Aging (NuAge),^18, 57^ n=2)
- Italy, n=2 (Monzino 80-plus study,^53^ n=1; InCHIANTI,^63^ n=1)
- Japan, n=2 (Ohsaki Cohort Study & Ohsaki Cohort 2006 Study,^40^ n=1; National Institute for Longevity Sciences-Longitudinal Study of Aging (NILS-LSA) project,^79^ n=1)
- Denmark, n=1 (Copenhagen General Population Study,^34^ n=1)
- Finland, n=1 (Cardiovascular Risk in Young Finns Study (YFS),^10^ n=1)
- Malaysia, n=1 (Long Term Research Grant Scheme-Towards Useful Ageing (LRGS-TUA),^41^ n=1)
- Portugal, n=1 (SWITCHBOX consortium,^59^ n=1)
- Scotland, n=1 (Lothian Birth Cohort 1936 (LBC1936),^16^ n=1)
- Multiple European Union countries (Belgium, France, Greece, Italy, Spain, Sweden, Switzerland, The Netherlands, UK), n=1 (European Prevention of Alzheimer’s Dementia Longitudinal Cohort Study (EPAD LCS),^28^ n=1)

#### Health Status

Participants across many studies were at high-risk for diet-related chronic disease based on either BMI, overweight or obesity, hypertension, or other cardiometabolic risk factors. Specifically, the RCT exclusively enrolled participants with a BMI ≥25 (mean=33.9 kg/m2) and family history of Alzheimer's disease, and approximately half of the participants also had a history of hypertension.^1^ Most observational studies reported mean BMI ≥25.0 kg/m2 of study participants,^2, 3, 5–8, 12, 13, 16–21, 24, 26, 31, 34, 36, 38, 42, 45–47, 49–52, 54–57, 59, 60, 63–65, 68, 69, 71, 72, 75–77^ but the full range included 21.3 kg/m2^83^ up to ~32 kg/m2.^7^ Several studies reported that ≥40% of the study participants had overweight and/or obesity.^4, 9, 23, 25, 35, 45, 58, 62, 67, 73, 77, 80^ One study exclusively enrolled participants with overweight/obesity or metabolic syndrome,^54^ and another exclusively enrolled those with CVD or 3+ CVD risk factors.^69^ Among studies that reported prevalence of HTN within the study sample (n=46), prevalence was generally ≥40%,^3, 7, 9, 12–15, 18–20, 23, 29, 33, 34, 45–49, 53, 54, 56–58, 64, 66, 67, 69, 71, 73, 76, 79, 80^ although it ranged from ~16%^17^ up to ~84%.^29, 54^

Many (n=38) observational studies excluded those with dementia, Alzheimer’s disease, cognitive impairment, and/or cognitive decline at baseline/exposure assessment.^2, 8, 9, 11–13, 15, 16, 20, 21, 23, 25, 26, 29, 33, 34, 36, 37, 39, 42, 47, 48, 50, 53, 56, 57, 59, 60, 63–65, 70–72, 75, 77, 79, 83^ Of the studies that did not specify excluding those with dementia, Alzheimer’s disease, cognitive impairment, and/or cognitive decline at baseline/exposure, few reported information on cognitive status at baseline. One reported that ~67% of the sample had subjective cognitive decline at baseline^70^; one reported that 11.1% had mild cognitive impairment at baseline^8^; and one reported that ~27% had an impaired MMSE score.^27^ Several additional studies reported family/parental history of dementia and/or Alzheimer’s disease: ~66% to 68% with family history of dementia^28^; 72.6% with parental history sporadic Alzheimer's disease^50^; 4.87% to 5.11% with family history of dementia^75^; ~2% with family Hx dementia^17^; 13.7% with family history of Alzheimer’s disease^77^; 20.6% with parental history of dementia.^76^

#### Race and/or Ethnicity

The included RCT enrolled majority (88%) White participants, with 11% Black participants and 1% “other.”^1^ Among the observational studies, many articles (n=20) reported that the majority (≥70%) of the analytic sample was non-Hispanic White^6, 9, 13, 17, 18, 23, 31, 33, 34, 39, 47, 48, 50, 62, 68, 69, 71, 73, 75–77^ while several (n=4) others mentioned that the majority of participants were white, although exact percentage was not reported.^22, 27, 44, 45^ Several articles reported exclusively enrolling those of Chinese ancestry (n=5),^11, 35, 66, 78, 82^ those of Japanese ancestry (n=2),^25, 79^ or those of Hispanic or Puerto Rican descent (n=3).^7, 43, 49^ Additionally, 5 articles from 3 unique cohorts in the United States reported enrolling majority racial/ethnic minorities: 42% non-Hispanic White, 11% Chinese, 25% non-Hispanic Black, 21% Hispanic^19^; 60% African-American, 40% White^38^; 63% African-American, 37% White^3^; 60% Black, 40% White in CHAP cohort^71^; 28.23% White, 29.44% Black, 40.36% Hispanic, 1.96% Other.^29^ Forty articles did not report data on race and/or ethnicity of the sample.

#### Socioeconomic position (SEP)

Participants across the body of evidence collectively represented a range of SEP, based primarily on educational attainment, although other indicators that were reported included household income, SES (e.g., Townsend index), cohabitation status, and occupational status/type. Participant education was reported in 79 of the 83 included articles and distributed as follows: low educational attainment or a mean of less than 12 years of education was reported in 26 articles,^4, 7, 8, 12, 13, 16, 18–21, 23, 26, 27, 29, 37, 41–43, 56, 61, 63, 68, 70, 74, 80, 83^ higher educational attainment and/or a mean of 12 years of education or more in 30 articles,^1–3, 9, 14, 15, 22, 24, 28, 31, 38, 39, 45–48, 50–53, 58, 59, 62, 64, 65, 71–73, 75, 76^ and a range of education levels across participants (e.g., 31% high school or less, 30% some college, 39% college degree or higher) were reported in 23 articles.^5, 6, 17, 30, 32–36, 40, 44, 49, 54, 55, 60, 66, 67, 77–79, 81, 82^ Only three included articles did not report any type of information regarding the SEP of participants.^11, 25, 57^ Fourteen articles^6, 7, 9, 17, 19, 32, 34, 37, 39, 41, 49, 74, 80, 83^ reported information on the household income, poverty-income ratio, and/or SES that indicated a majority of participants had lower or a range of SES (e.g., ≥ 50% of participants with low household income^34, 74^; ~20–30% of participants at each income level.^9, 19, 80^

### Intervention/exposure and Comparator

Dietary pattern consumption was examined among participants at a mean age of 11 years^10^ up to 92 years.^53^ Thirty-eight articles analyzed samples with a mean age ≥70 years; 51 studies analyzed samples with a mean age ≥65 years, while 63 studies analyzed samples with a mean age ≥60 years. One study examined the relationship between dietary patterns consumed during both childhood and adulthood, and subsequent cognitive decline in adulthood,^10^ while all other included studies examined dietary patterns during adulthood only. The majority of articles from observational studies (n=59) assessed dietary intake once at baseline, while 21 used repeated assessments and 2 used only baseline data after testing that change in dietary intake was minimal.^47, 73^ The most common diet assessment method was FFQ and/or other food screeners (n=59)^2, 3, 5, 7–9, 11–16, 18–22, 24, 29–31, 33–40, 42–48, 50–55, 57, 58, 63–65, 67–71, 73, 74, 76, 78, 81–83^ followed by 24-hour dietary recall (n=12)^84^, diet history or other health questionnaires (n=6),^4, 23, 28, 41, 60, 72^ diet records (n=2), or some combination of methods (n=6).^10, 26, 35, 66, 78, 82^

Dietary pattern methods included:

- Intervention: 1 article
- Index/Score analysis: n=71
- Factor/cluster or latent-class analysis: n=14
- Reduced Rank Regression: n=2

A visualization of all dietary pattern components in each dietary pattern examined in relation to outcomes of interest is available in Appendix 6: Dietary pattern visualization.

### Outcome

Studies used various methods to assess cognitive outcomes:

- Cognitive decline and/or mild cognitive impairment outcomes were reported in 60 articles.^1–3, 5, 7, 8, 10, 12–19, 22, 24, 27, 28, 30, 32, 33, 35, 37–39, 41, 43–47, 49–52, 54–59, 61, 63, 64, 66–74, 76, 78, 80–83^
  ○ Cognitive function was most often assessed using researcher-administered, domain-specific tasks (n=10) that were reported separately and/or combined to create a researcher-defined global/composite cognitive function score. Cognitive questionnaires were also commonly used (e.g., Montreal Cognitive Assessment; Cognitive Abilities Screening Instrument; MMSE; TICS-M, n=4), or a combination of both cognitive tasks and questionnaires (n=9).
  ○ Cognitive decline and mild cognitive impairment were most often assessed using cognitive questionnaires that applied pre-determined cutoff values to define cognitive impairment/decline (n=17) and/or assessed change across 2 or more time points (n=11). The Mini-Mental State Examination (MMSE) or an adapted version of it was the most commonly used questionnaire, either used as a standalone measure (n=16) or in combination with other measures (n=6). Cognitive decline and/or impairment was also assessed using other cognitive questionnaires (e.g., TICS-M, n=9; Cognitive Abilities Screening Instrument, n=1; Montreal Cognitive Assessment, n=1), change in cognitive domains (n=6), or a combination of both (n=3). Subjective measures of cognitive decline and/or mild cognitive impairment were reported in 3 articles, though little additional information was provided.
- Risk of dementia (26 articles^4, 6, 8, 11, 17, 20, 21, 23, 25, 26, 29, 31, 34, 36, 40, 41, 53, 56, 60, 62, 65, 71, 75, 77, 79, 80^) and/or Alzheimer’s Disease (11 articles^4, 6, 17, 23, 25, 26, 34, 42, 48, 56, 71^) were most often assessed using data obtained from medical insurance databases, medical/hospital records, and/or death records (n=16). Additional methods included researcher/expert diagnosis based on performance on cognitive screening tools and/or tasks (n=9) and MMSE scores (n=3).

## Synthesis of the evidence

Statistically significant associations between dietary patterns and [underlined: lower risk of] cognitive decline, dementia, Alzheimer’s disease, and/or mild cognitive impairment were reported in 54 articles (all from observational studies^2–5, 7–10, 15, 17, 20, 22, 24, 28, 32–35, 37–43, 45, 47, 48, 51, 52, 54, 55, 58, 59, 61–67, 70–76, 78–80, 82, 83^). These dietary patterns were generally characterized by a higher intake of vegetables (often excluding potatoes), fruits, legumes, nuts, fish/seafood, unsaturated vegetable oils/fats, and lower intakes of red and processed meats and sugar-sweetened beverages. These dietary patterns included dairy and/or dairy products as well as alcoholic beverage components, but varied considerably in scoring procedures and specificity of components. Many of the dietary patterns included a grains/cereals component scored positively, but varied considerably in whether intake was specifically from whole grains, other cereals/grains, or total grains collectively.

“Mediterranean” dietary pattern scores were assessed in 34 articles and significantly associated with lower risk of adverse cognitive outcomes in 24 articles, including better cognitive function/lower risk of cognitive decline (n=17),^2, 3, 8, 24, 28, 33, 43, 54, 55, 58, 59, 63, 64, 67, 72, 76, 82^ as well as lower risk of dementia (n=6),^4, 8, 20, 62, 65, 70^ Alzheimer’s Disease (n=2),^42, 48^ and mild cognitive impairment (n=1).^33^ No statistically significant associations between Mediterranean dietary pattern scores and cognitive outcomes were reported in 10 articles. Dietary patterns shared the following components positively scored: vegetables (not potatoes), fruit, legumes, nuts, cereals/whole grains, fish, and unsaturated vegetable oils/fats; and; positive or positive in moderation: alcoholic beverages; and negatively scored: red and processed meat, sugar-sweetened beverages.

- Several of these studies reported statistically significant results with at least one outcome, but not all results across cognitive outcomes reached statistical significance. For example, a Mediterranean dietary pattern was associated with lower risk of cognitive decline based on one cognitive test (Four Mountains Test) but was not associated with cognitive decline assessed using a different test (Repeatable Battery for the Assessment of Neuropsychological Status).^28^
- Several articles reported associations between Mediterranean-style dietary patterns and cognitive outcomes by additional factors such as age or health status. For example, in one of these articles, a Mediterranean dietary pattern score was associated with lower risk of cognitive decline in those ≥70 years old but was not associated with cognitive decline in those <70 years old.^72^ However, other articles did not report associations between Mediterranean dietary patterns and cognitive outcomes by age, and there does not appear to be a trend across studies by age. Several articles stratified groups by various health markers and found differences in the association between Mediterranean diet and cognitive outcomes. One article found that Mediterranean dietary patterns were associated with a lower risk of Alzheimer’s disease in those at low genetic risk for Alzheimer’s disease, but no association was found for those at high genetic risk.^42^ Another article found that a Mediterranean dietary pattern was associated with better cognitive function in those with type 2 diabetes, but no association was found for those without type 2 diabetes.^43^ Lastly, one article found that lower adherence to a Mediterranean dietary pattern was associated with greater cognitive decline in those with hypertension, although this association was not significant in those without hypertension.^58^

Mediterranean-Dash Intervention for Neurodegenerative Delay (MIND) dietary patterns were assessed in 14 observational articles and 1 RCT,^1^ and associated with lower risk of adverse cognitive outcomes in 10 articles, including better cognitive function/lower risk of cognitive decline (n=7),^7, 17, 22, 47, 52, 71, 73^, lower risk of dementia (n=3),^9, 20, 71^ and lower risk of Alzheimer’s’ disease (n=2).^48, 71^ None of these articles examined risk of mild cognitive impairment. The MIND score used in most of these studies similarly scored the following components positively: vegetables (especially green leafy), beans, berries, nuts, whole grains, seafood, poultry, olive oil; positive or positive in moderation: wine; and negatively: red meat, cheese, pastries and sweets, butter and stick margarine, fried/fast food.

- One of these articles examined data from multiple cohorts and found that a MIND dietary pattern was not associated with cognitive outcomes (cognitive decline, dementia, Alzheimer’s disease) in a majority-Black (60%) cohort but was associated with better cognitive outcomes in a different cohort, of which the racial/ethnic composition was not reported.^71^
- Conversely, another article reported that MIND dietary pattern adherence was associated with lower risk of dementia in a cohort that was ~70.5% White, 15.4% Black, 10.8% Hispanic, and 3.3% other, but no association was found within a cohort that was primarily (90.9%) White.^9^
- One RCT examined the effect of a MIND dietary pattern versus a control (usual) dietary pattern, both of which emphasized a 250 kcal/d energy deficit, on change in global cognitive function. No difference was found in change in global cognitive function between the two dietary patterns.^1^

‘DASH’ style scores were examined in 13 articles and were significantly associated with lower risk of adverse cognitive outcomes in 7 articles, including better cognitive function/lower risk of cognitive decline (n=6)^35, 43, 54, 64, 76, 82^ and lower risk of mild cognitive impairment (n=1).^66^ Most of these results included “DASH”-style indices that similarly scored the following components positively: vegetables (not potatoes), nuts and legumes, fruit and fruit juice, whole grains, dairy; and negatively: red and processed meat, sugar-sweetened beverages, sodium. One of these studies found that a DASH dietary pattern was associated with better cognitive function in those without type 2 diabetes, but no association was found in those with type 2 diabetes.^43^ However, no statistically significant associations were reported between DASH scores and risk of dementia and/or Alzheimer’s disease.

Dietary Guidelines-related scores (e.g., Healthy Eating Index) were examined in 12 articles and associated with lower risk of adverse cognitive outcomes in 8 articles, including better cognitive function/lower risk of cognitive decline (n=7),^15, 17, 39, 43, 52, 76, 82^ and lower risk of dementia (n=1).^65^ However, no statistically significant associations were reported between Dietary Guidelines-related scores and Alzheimer’s disease or mild cognitive impairment. These articles generally scored the following dietary pattern components positively: vegetables (not potatoes, French fries), fruit, legumes and nuts, whole grains; and negatively: added sugars/sugar-sweetened beverages, red and processed meats.

- One study found that both Alternative Healthy Eating Index, 2010 and Healthy Eating Index 2015 scores were each associated better cognitive function in select domains in those without type 2 diabetes but were not associated with global cognitive function (in those with or without type 2 diabetes).^43^

Country-specific dietary patterns scores were examined in 9 articles, including the Japanese Dietary Index (n=2),^40, 79^ adherence to the Danish Dietary Guidelines (n=1),^34^ the Dietary Guideline Index for Australia (n=2),^12, 46^ the Swiss Dietary Guidelines Score (n=1),^26^ China Elderly Dietary Guidelines Index (n=1),^32^ Chinese Dietary Guidelines Index (n=1),^81^ and adherence to the Dutch Dietary Guidelines (n=1).^20^ These dietary patterns were associated with lower risk of adverse cognitive outcomes in 5 articles, including lower risk of dementia (n=3),^34, 40, 79^ lower risk of mild cognitive impairment (n=1)^81^ and better global cognition (n=1).^32^ Articles varied considerably in the dietary pattern components, but generally scored the following positively: vegetables, fruit; positively or moderately: fish/seafood; and negatively or moderately: meats (all, red, and/or processed).

- In one of these articles, one variation of a Japanese Diet Index was associated with lower risk of dementia, though three different variations were not. Compared to the variations not associated with dementia risk, the dietary pattern associated with lower dementia risk emphasized higher intake of mushrooms, moderate (rather than high) intake of rice, and did not emphasize intake of pickles or coffee.^79^ Another article found that lower adherence to the Danish Dietary Guidelines was associated with higher risk of dementia but not Alzheimer’s disease.^34^ In one article examining results by age group, adherence to the China Elderly Dietary Guidelines Index was associated with better global cognition in those <65 years old at baseline, but not in those ≥ 65 years at baseline.^32^

Other index/score analyses were examined in 16 articles and were associated with lower risk of adverse cognitive outcomes in 9 articles, including lower risk for cognitive decline or cognitive impairment (n=8)^37, 38, 45, 55, 74, 78, 82, 83^ and lower risk of dementia (n=1).^75^ The majority of these articles (n=5) included a plant-based dietary index,^37, 38, 75, 82, 83^ which emphasizes intake of vegetables (including potatoes), fruits, nuts, legumes, grains (whole and refined), tea & coffee, and vegetable oils and negatively scores animal fats, dairy, eggs, fish/seafood, and meat (poultry and red meat). Other dietary patterns associated with lower risk for adverse cognitive outcomes similarly scored the following components positively: vegetables, legumes, fruit, and grains; and negatively: saturated/animal fats and meat (red and/or poultry). Fish and/or seafood and dairy were mixed, with some dietary patterns scoring positively and some scoring negatively.

Dietary patterns examined by factor/cluster analysis or reduced-rank regression were examined in 11 articles and associated with lower risk of adverse cognitive outcomes in 6 articles, including lower risk of dementia (n=1)^41^ and better cognitive function/lower risk of cognitive decline (n=5).^5, 10, 51, 61, 80^ Though the dietary components varied widely across these studies, they commonly scored the following components positively: vegetables, fruits, and legumes.

Dietary patterns related to [underlined: higher risk] of adverse cognitive outcomes in 5 articles from observational studies, including higher risk of cognitive decline/poorer cognitive function (n=3),^51, 57, 83^ higher risk of cognitive impairment (n=1),^37^ and higher risk of dementia (n=1).^75^ Three of these studies used index/score analysis to examine dietary patterns, specifically an unhealthy plant-based dietary pattern,^37, 75, 83^ while two others used factor/cluster to derive what both authors described as a "Western-style" dietary pattern.^51, 57^ Though there was considerable variability in the components of these dietary patterns, they generally scored the following components positively: refined grains, sugar-sweetened beverages, and sweets/desserts.

## Conclusion statement and grade

The 2025 Dietary Guidelines Advisory Committee updates the existing systematic review, updated by the 2020 Dietary Guidelines Advisory Committee, by synthesizing an additional 83 articles that were published between March 2020 and January 2024 and met inclusion criteria, as well as studies that were previously excluded but met updated inclusion criteria (see Table 5).

Table 5 Conclusion statement, grade for dietary patterns and risk of cognitive decline, dementia, Alzheimer’s disease, and mild cognitive impairment.

Conclusion Statement | Dietary patterns consumed by adults and older adults that are characterized by higher intakes of vegetables, fruits, legumes or beans, nuts, fish and/or seafood, and unsaturated vegetable oils/fats and lower in red and processed meats and sugar-sweetened beverages, are associated with lower risk of age-related cognitive decline, mild cognitive impairment, dementia and/or Alzheimer’s disease. This conclusion statement is based on evidence graded as moderate. (Grade: Moderate)
Grade | Moderate
Body of Evidence | 83 articles: 1 from intervention (RCT); 82 from observational studies (OBS)
Consistency | Some concerns with minimal variability in direction, but minimal to moderate variability in the magnitude of results.
Precision | Serious concerns regarding only one RCT eligible. Confidence intervals ranged from narrow to wide across reported results from observational studies.
Risk of bias | Serious concerns due to potential confounding, exposure misclassification, and outcome measurement error.
Directness | Few concerns with directness of: populations, intervention/exposure, comparators. Some concerns with directness of outcome assessment.
Generalizability | The dietary patterns, outcomes, and participant characteristics are applicable to the U.S. population.

### Assessment of the Evidence

This systematic review update includes 83 articles that met inclusion criteria and examined the relationship between dietary patterns and risk of cognitive decline, dementia, Alzheimer's disease, and mild cognitive impairment. Dietary patterns were assessed using a variety of methods, primarily indices or scores, but also factor/cluster analysis, reduced rank regression, and 1 experimental diet. Outcomes were determined from various methods including domain-specific cognitive tasks, cognitive screeners and/or questionnaires, and linkage to medical/hospital records, death records, and insurance databases. As outlined and described below, the body of evidence was assessed for the following elements used when grading the strength of evidence. This body of evidence includes both large and small studies (with significant as well as null findings) so publication bias may be less likely.

#### Consistency:

The direction of findings was relatively consistent across observational studies. Out of 82 observational studies, 54 found statistically significant associations between dietary patterns and [underlined: lower risk of] cognitive decline, dementia, Alzheimer’s disease, and/or mild cognitive impairment. These dietary patterns were generally characterized by higher intake of vegetables (typically excluding potatoes), fruits, legumes, nuts; and lower intakes of red and processed meats and sugar-sweetened beverages. A small sub-set of evidence supported associations between dietary patterns higher in refined grains, sugar-sweetened beverages, and sweets/desserts and higher risk of cognitive decline/poorer cognitive function, higher risk of cognitive impairment, and higher risk of dementia. However, the RCT did not support these findings, as it found no effect of MIND diet, which emphasized intake of green leafy vegetables, total vegetables, beans, berries, nuts, whole grains, seafood, poultry, olive oil, and wine, and lower intake of red meat, cheese, pastries and sweets, butter and stick margarine, and fried/fast food, on cognitive decline when compared to a control diet, both of which also included a calorie reduction component.

#### Precision:

This body of evidence included 83 articles, only 1 of which was an RCT. Among the observational studies, sample sizes ranged from 76 up to 180,532, with most including <10,000 participants in analyses. Significance of the results did not seem depended on sample size, although the width of confidence intervals varied across studies, with moderate to large variances.

#### Risk of bias

Studies had variable risks of bias across domains, which have the potential to influence the results reported. Many articles did not control for several key confounders, leading to a ‘high’ or ‘very high’ risk of bias in Domain 1 (confounding) for 42 of 82 observational articles. Many articles also assessed dietary intake at only one time point, leading to ‘some concerns’ of possible exposure misclassification in Domain 2. Many articles were at ‘some concerns’ or ‘high’ risk of bias of the outcome measurement, Domain 6, due to concerns with the validity of measurements and/or only more severe cases being represented (e.g., use of hospital records). Observational studies rarely had a pre-specified analysis plan and/or sometimes conducted multiple exposure and outcome analysis, which also resulted in a higher risk of bias for selection of reported results.

#### Directness:

Studies and/or analyses were designed to directly examine the relationship between dietary patterns and risk of cognitive outcomes. Few concerns were noted with directness of populations, intervention/exposure, and comparators used to examine this relationship. However, some concerns were noted with the directness of outcomes measured as they relate to the outcomes of interest.

#### Generalizability:

Many articles (n=29) were published using data collected in the United States, including 1 RCT and observational data from 19 unique cohorts. Other studies are applicable to the U.S. population based on participant characteristics, including racial/ethnic background and health status, intervention/exposure vs. comparators, and/or outcomes. Several observational articles reported exclusively enrolling those of racial and/or ethnic minority: Chinese ancestry (n=5);^11, 35, 66, 78, 82^ Japanese ancestry (n=2);^25, 79^ Hispanic or Puerto Rican descent (n=3).^7, 43, 49^ Additionally, 5 articles from 3 unique cohorts in the United States reported enrolling majority racial and/or ethnic minorities: 42% non-Hispanic White, 11% Chinese, 25% non-Hispanic Black, 21% Hispanic^19^; 60% African-American, 40% White^38^; 63% African-American, 37% White^3^; 60% Black, 40% White in CHAP cohort^71^; 28.23% White, 29.44% Black, 40.36% Hispanic, 1.96% Other.^29^ Many participants in this body of evidence were at high-risk for diet-related chronic disease based on cardiometabolic risk factors such as high-BMI and hypertension. However, studies also included those without these risk factors and therefore, results are generalizable to the U.S. population. Most of the dietary patterns examined are applicable to those consumed by Americans, with some exceptions for country-specific dietary patterns that include foods such as seaweed and algae, which are not commonly consumed by many Americans. Outcomes examined were also applicable to the United States population.

## Research recommendations

1. Future studies should examine dietary patterns at multiple time points across the lifespan and their relationship to cognitive outcomes and/or dementia. Until the critical time point(s) during which dietary patterns may affect age-related cognitive decline and/or dementia are identified, reliance on a single measure of exposure (dietary patterns) in middle age to older adulthood may have limited validity. For example, dietary patterns may be subject to change as cognitive function declines, leading to concerns with reverse causality. Also, few studies examine dietary patterns during childhood, adolescence, and/or younger adulthood in relationship to cognitive decline in later life.
2. Articles used a variety of outcome assessment methods/tools, some of which may be of limited validity and/or at high risk of bias, limiting the ability to compare findings across publications. Focus should be placed on creating a consensus on the most valid and reliable measures of cognitive outcomes and subsequent research should prioritize using these methods.
3. Many articles controlled only for education, without controlling for other metric(s) of SEP. Because education and SEP are likely independently related to both the exposure (dietary patterns) and outcomes of cognition, future research should control for both of these variables.
4. Future studies should assess and control for genetic risk factors for cognitive outcomes (e.g., Apolipoprotein E genotype), as they may confound the relationship between dietary patterns consumed and cognitive outcomes of interest.
5. In addition to more robust observational studies that address the limitations above, more RCTs are needed in order to determine the relationship between dietary patterns consumed and cognitive outcomes.

Table 6 Evidence examining the relationship between dietary patterns consumed by adults and older adults and risk of cognitive decline, dementia, Alzheimer’s disease, and mild cognitive impairment^*^ * Abbreviations: AD, Alzheimer’s disease; Alz, Alzheimer’s disease; BMI, body mass index; CD, cognitive decline; CDT, clock drawing test; CFx, cognitive function; CI, confidence interval; CVD, cardiovascular disease; DASH, Dietary Approaches to Stop Hypertension; Dem, dementia; DG, dietary guidelines; DM, diabetes mellitus; DP, dietary pattern(s); DSM, Diagnositc and Statistical Manual; Dx, diagnosis; Dz, disease; EF, executive function; f/u, follow-up; FFQ, food frequency questionnaire; Fx, function; GCFx, global cognitive function; h, hour(s); HH, household; HR, hazard ratio; HTN, hypertension; Hx, history; IHD, ischemic heart disease; Kcal, kilocalories; LF, low-fat; LFU, lost to follow-up; MCI, mild cognitive impairment; MIND, Mediterranean-Dash Intervention for Neurodegenerative Delay; MMSE, mini mental state examination; mo, month(s); MUFA, monounsaturated fatty acids; n/a, not available; NH, non-Hispanic; NHANES, National Health and Nutrition Examination Survey; NHS, Nurses’ Health Study; NIA, National Institutes of Aging; NIH, National Institutes of Health; NR, not reported; NS, non-significant; OR, odds ratio; PCA, principal component analysis; PUFA, polyunsaturated fatty acids; Q, quartile; RCT, randomized controlled trial; Ref, reference; SD, standard deviation; SE, standard error; SEP, socioeconomic position; SFA, saturated fatty acids; SNAP, supplemental nutrition assistance program; STICS-m, Spanish version of the modified Telephone Interview for Cognitive Status; T, tertile; TEI, total energy intake; TEI, total energy intake; TIA, transient ischemic attack; TICS, Telephone Interview for Cognitive Status; TICS-m, modified Telephone Interview for Cognitive Status; wk, week(s); y, year(s)

Article Information | Intervention/exposure and comparator | Results | Methodological considerations
Randomized Controlled Trial
Barnes, 2023 ^1^; United States; n/a; Analytic N=571 (6 mo); 560 (1 y); 552 (2 y); 564 (3 y); Participant characteristics:; - [underlined: Race and/or Ethnicity]:∼88% White; ∼11% Black; ∼1% Other; - [underlined: SEP]: Education, ∼17 y (mean); - [underlined: Selection]: Included those with score of 22+ on Montreal Cognitive Assessment (low or no cognitive impairment); those with BMI ≥25; those with family Hx Alzheimer’s dementia; with suboptimal diets (MIND score ≤8); included participants had to agree not to take vitamins (e.g., folate, multivitamins) and to complete a 3–4 wk run-in period. Excluded those with nuts, berries, olive oil, or fish allergies; use of medication to treat Alzheimer’s Dz or Parkinson’s Dz; with psychosis or bipolar disorder; with depression or other psychiatric disorder that my interfere w participation; psychiatric medication; alcohol or substance abuse, or heavy alcohol consumption; recent CVD, stroke, TIA, cancer; Hx of brain injury, liver Dz, HIV, Hep-C | DP Age(s): 65+ y at baseline (70.4 y mean); DP Components:; - MIND Diet: Positive: Green leafy vegetables; Vegetables; Beans; Berries; Nuts; Whole Grains; Seafood; Poultry; Olive oil; Wine. Negative: Red Meat; Cheese; Pastries and sweets; Butter and stick margarine; Fried/fast food. Slight (∼250 kcal/day) energy deficit; - Control diet: usual diet + slight (250 kcal/day) energy deficit; - DP Method(s): RCT; Comparisons: MIND diet vs. control diet (higher MIND score mean 11 vs. 8.5 [or by 3.3 vs. 0.7 pt.]) | Follow-Up Duration: 6 mo, 1 y, 2 y, 3 y; Results:; ΔGlobal cognition, 6 mo; MIND diet, 0.125, 95% CI: 0.093, 0.158; Control, 0.117, 95% CI: 0.085, 0.149; Difference, 0.008, 95% CI: −0.037, 0.054; ΔGlobal cognition, 1 y; MIND diet, 0.226, 95% CI: 0.188, 0.264; Control, 0.211, 95% CI: 0.173, 0.248; Difference, 0.015, 95% CI: −0.038, 0.069; ΔGlobal cognition, 2 y; MIND diet, 0.246, 95% CI: 0.205, 0.287; Control, 0.200, 95% CI: 0.159, 0.240; Difference, 0.046, 95% CI: −0.011, 0.104; ΔGlobal cognition, 3 y; MIND diet, 0.205, 95% CI: 0.164, 0.246; Cotrol, 0.170, 95% CI: 0.130, 0.210; Difference, 0.035, 95% CI: −0.022, 0.092; p=0.23; Summary: Null: MIND diet group vs. control diet & ΔGlobal cognition | - Small improvements in global cognition in both groups (could be learning effect over time); control group had slightly higher % of participants with APOE-ε4 allele; - Diet assessment: RCT: adherence to MIND diet assessed via MIND-diet questionnaire & biomarkers; - Outcome measurement: Raw score from multiple tests (below) converted to z-scores, then z-scores averaged across all tests to create global composite score; - Tests used: Episodic memory ((Word List Memory, Word List Recall, Word List Recognition,15 East Boston Story Immediate Recall, & East Boston Story Delayed Recall); Semantic memory (Category Fluency [animals and fruits and vegetables] & Multilingual Naming Test); Executive function (Trail Making Test B & Flanker Inhibitory Control and Attention Test from NIH toolbox); Perceptual speed (Oral Symbol Digit Modality Test, Pattern Comparison Test, & Trail Making Test A); - Funding: NIA
Observational Studies
Agarwal, 2021 ^3^; United States; Chicago Health and Aging Project; Analytic N=5001; Participant characteristics:; - [underlined: Race and/or Ethnicity]:63% ‘African-Amercian’; 37% White; - [underlined: SEP]: Education, 12.5y mean; - [underlined: Selection:] Excluded those with missing FFQ; <2 cognitive assessments; implausible/extreme BMI or TEI; aged <65 y | - DP Age(s): ∼74y (SD: 6); ≥65y at baseline; - DP(s) examined: Mediterranean-based Diet Score (MedDietScore) [Panagiotakos 2007]; Western DP; - DP Components:; - MedDietScore, Positive: Vegetables; Potatoes; Legumes; Fruit; Whole Grains; Fish; Olive Oil. Negative: Red and Processed Meat; Poultry; Full-Fat Dairy; Alcohol; - Western DP, Higher in fried foods, refined grains, sweets, red and processed meats, full fat dairy, and pizza; - DP Method(s): Index/Score; Factor/Cluster; Comparisons: Categorical, Western DP High (>3.5) vs. Low (<3.5); MedDietScore, tertiles (T1, ref) | Follow-Up Duration: 6.3 y (SD: 2.8), mean; Results:; MedDietScore & CD, β (95% CI); T2, 0.003 (−0.004, 0.011); T3, 0.015 (0.006, 0.023); p-trend=0.0006; NS, MedDietScore*Western DP & CD, p=0.13; MedDietScore & CD among those with Low Western DP, β (95% CI); T2, 0.013 (0.02, 0.024); T3, 0.019 (0.007, 0.032); p-trend=0.003; MedDietScore & CD among those with High Western DP, β (95% CI); T2, −0.007 (−0.019, 0.005); T3, 0.010 (−0.002, 0.022); p-trend=0.09; Summary: Inverse: MedDietScore & CD; Inverse: MedDietScore* Low Western DP & CD; NS/Null: MedDietScore* High Western DP & CD | - Did not account for: SEP; Anthropometry; - Anthropometry not controlled for but BMI seems similar across tertiles; - Diet assessment: FFQ assessed every cycle (∼3y); - Outcome measurement: CD: rate of change in global cognitive scores from avg. z-score of combined MMSE; East Boston (immediate; delayed); and Symbol Digit); Episodic memory avg. z-score from East Boston (immediate; delayed); Perceptual memory from z-score of Symbol Digit; Funding: NIA; NIH
Andreu-Reinón, 2021 ^4^; Spain; European Prospective Investigation into Cancer and Nutrition (EPIC) Spain; Analytic N=16160; Participant characteristics:; - [underlined: Race and/or Ethnicity: NR]; - [underlined: SEP]: Majority with low education level (primary school or less), 71.4% (non-cases), ∼88.6% (cases); - [underlined: Selection]: Excluded those pregnant or breastfeeding; not being physically or mentally capable of participating; with major chornic pathology (DM, IHD, stoke, cancer); extreme energy intake; | - DP Age(s): 48.3 y (non-cases), ∼59–60 y (cases); 30–70 y at baseline; mean at baseline; - DP(s) examined: relative Mediterranean Diet Score (rMED) [Buckland 2009]; - Mediterranean Diet Score (MDS) [Trichopolou 2003]; - Alternate Med Diet Score (aMED) [Fung 2005]; - adapted relative Mediterranean Diet score (arMED) [Buckland, 2012]; - DP Components:; - rMED, Positive: Vegetables (not potatoes); Legumes; Fruit, Nuts, and Seeds (not juice); Whole Grains, Refined Flour, Pasta, Rice, Bread, Grains; Fish; Olive Oil. Negative: Total and Processed Meat. Neutral: Alcohol; - MDS, Positive: Vegetables; Legumes; Fruit, Nuts; Cereals; Fish; MUFA/SFA. Negative: Red and Processed Meat; Dairy Products. Neutral: Alcohol; - aMED, Positive: Vegetables (not potatoes); Legumes; Fruit; Nuts; Whole Grains; Fish; MUFA/SFA. Negative: Red and Processed Meat. Neutral: Alcohol; - arMED, Positive: Vegetables (not potatoes); Legumes; Fruit, Nuts, and Seeds (not juice); Cereals; Fish; Olive Oil. Negative: Meat; Dairy Products; - DP Method(s): Index/Score; - Comparisons: Categorical, low (0–6pts), medium (7–10pts), high (11–18pts); Continuous, per 2-pt | Follow-Up Duration: 21.6 y (mean); Results:; rMED & Dem, all-cause + Alz; (95% CI); Low, HR: 1, ref; Medium, HR: 0.85 (0.66, 1.09); High, HR: 0.80 (0.60, 1.06); Per 2-pt, HR: 0.92 (0.85, 0.99); p-trend (linear)=0.021; p-trend (non-linear)=0.094; arMED & all-cause dementia, similar effects to rMED (data NR); MDS & all-cause dementia, results attentuated compared to rMED (data NR); aMED & all-cause dementia, NS (data NR); rMED & Dem, non-Alz; (95% CI); Low, HR: 1, ref; Medium, HR: 0.64 (0.41, 0.99); High, HR: 0.68 (0.42, 1.10); Per 2-pt, HR: 0.87 (0.77, 0.99); p-trend (linear)=0.037; p-trend (non-linear)=0.098; rMED & Alz (95% CI); Low, HR: 1, ref; Medium, HR: 0.98 (0.71, 1.33); High, HR: 0.87 (0.61, 1.24); Per 2-pt, HR: 0.94 (0.86, 1.03); p-trend (linear)= 0.196; p-trend (non-linear)=0.353; Summary: Inverse: rMED & Dem, non-Alz (low vs. medium, cont.); Inverse: rMED & Dem, all-cause (cont.); NS/Null: rMED & Dem, all-cause (categorical); NS/Null: rMED & Alz (categorical & cont.) | - Did not account for: SEP, Race and/or Ethnicity; - Data not fully reported for other index/scores (MDS; aMED; arMED); When stratified by sex, rMED & allcause Dem, non-Alz dementia significant only for women.; - Diet assessment: Diet Hx once at baseline (interviewer-administed); - Outcome measurement: Dementia & Alzheimer’s Dz obtained via medical records, hospital discharge databases, and regional mortality registries; Funding: International Agency for Research on Cancer; European Commission; Health Research Fund (FIS) of the Spanish Ministry of Health; Red Temática de Investigación Cooperativa de Centros de Cáncer; CIBER de Epidemiología y Salud Pública (CIBERESP); Regional Governments of Andalusia, Asturias, Basque Country, Murcia, and Navarra; Catalan Institute of Oncology (ICO)
Ashby-Mitchell, 2015 ^5^; Australia; Australian Diabetes, Obesity and Lifestyle Study (AusDiab); Analytic N=577; Participant characteristics:; - [underlined: Race and/or Ethnicity: NR]; - [underlined: SEP]: Education: 24% secondary, 40% tertiary, 17% technical/primary only; - [underlined: Selection:] Excluded those with or who had missing dietary or cognitive data, < 60 y at baseline | - DP Age(s): 66 y, mean (60 to 83y, Wave 1 range at baseline); - DP(s) examined: n/a; - DP Components:; - 101, DP1, Fruit & Vegetable: Positive loadings: carrots; onion; beetroot; pumpkin; mango; zucchini; avocado; peaches; apricots; crackers; potatoes; peas; broccoli, cabbage, multigrain bread; - 101, DP2, Snack & Processed: Positive loadings: potatoes, cakes, jam, ice cream, sweet buscuits, salami, sausages, chocolate, sugar, meat pies, vegemite; - 101, DP3, Vegetable: Positive loadings: avocado; lettuce; cucumber; capsicum; celery; tomatoes; yogurt; Negative: sugar; peas; chips; white bread; - 101, DP4, Meat: Positive loadings: pork, veal, lamb, beef, chicken, peanut butter, soft cheese; - 101, DP5, Fish, Legumes & Vegetable: Positive loadings: Fish, other beans, tofu, spinach, baked beans, tinned fish, ricotta or cottage cheese, musrooms, bean sprouts, strawberries, fried fish, soy milk; - 101, DP6, Vegetable, Pasta & Alcohol: Positive: Red wine; pasta; spirits; cornflakes; Negative: cauliflower, broccoli, cabbage; - 101, DP7, Dairy, Cereal & Eggs: Positive loadings: Crackers, low-fat cheese, tinned fruit, cornflakes, fruit juice, all bran; Negative: full cream milk, eggs, butter/margarine spreads; - 32, DP1, Western: Positive: Red Meats; Snacks; Refined Grains; Poultry; Condiments; Meat Pies; Chips/French Fries; Beer; Pizza; - 32, DP2, Prudent: Positive: Other Vegetables; Green Leafy Vegetables; Fruit; Garlic and Onions; Fish; Nuts; Tomatoes; - 32, DP3, Vegetable, Grain, Wine: Positive: Snacks; Condiments; Dark Yellow Vegetables; Potatoes; Cruciferous Vegetables; Whole Grains. Negative: Wine; - 32, DP4, High-Fat: Positive: High Fat Dairy Products; Butter; Butter and Margarine Blends; Eggs. Negative: Low Fat Dairy Products; Margarine; - 20, DPI, Variety: Positive: Vegetables; Fish; Fruit; Whole grains; Nuts; Poultry; Condiments; Meat; Fruit Juice; - 20, DP2, Western: Positive: Snacks; Sugar; Fats and Oils; Meat Pies; Chips/French Fries. Negative: Legumes; - 20, DP3, Dairy, Grain, Alcohol: Positive: Meat, Alcohol, Refined Grains; Negative: Dairy; Whole grains; - DP Method(s): Factor/Cluster; Comparisons: Continuous, each DP per unit increase | Follow-Up Duration: ∼12 y total Results:; DP, 101 items & CD, OR (95% CI); DP1, OR: 1.061 (1.006, 1.118); p=0.030; DP2, OR: 1.051 (0.967, 1.143); p=0.239; DP3, OR: 0.986 (0.916, 1.061); p=0.701; DP4, OR: 1.005 (0.964, 1.048); p=0.806; DP5, OR: 1.032 (1.001, 1.064); p=0.040; DP6, OR: 1.000 (0.965, 1.037); p=0.994; DP7, OR: 1.020 (1.007, 1.033); p=0.003; DP, 32 items & CD, OR (95% CI); DP1, OR: 1.005 (0.994, 1.016); p=0.409; DP2, OR: 0.997 (0.984, 1.010); p=0.643; DP3, OR: 1.008 (0.995, 1.020); p=0.229; DP4, OR: 0.999 (0.992, 1.007), p NR; DP, 20 items & CD, OR (95% CI); DP1, OR: 1.006 (0.994, 1.018); p=0.333; DP2, OR: 1.008 (0.986, 1.031); p=0.497; DP3, OR: 1.001 (0.998, 1.005); p=0.383; Summary: NS/Null: 101-itemDP2, Snack & Processed & CD; NS/Null: 101-item DP3, Vegetable & CD; NS/Null: 101-item DP4, Meat & CD; NS/Null: 101-item DP6, Vegetable, Pasta & Alcohol & CD; NS/Null: 32-item DP1, Western & CD; NS/Null: 32-item DP2, Prudent & CD; NS/Null: 32-item DP3, Vegetable, Grain, Wine & CD; NS/Null: 32-item DP4, High-Fat & CD; NS/Null: 20-item DP1, Variety & CD; NS/Null: 20-item DP2, Western & CD; NS/Null: 20-item DP3, Dairy, Grain, Alcohol & CD; Inverse: 101-item DP1, Fruit & Vegetable & CD; Inverse: 101-item DP5, Fish, Legumes & Vegetable & CD; Inverse: 101-item DP7, Dairy, Cereal & Eggs & CD | - Did not account for: SEP, Race and/or Ethnicity; - Additional outcomes reported include Memory, Vocabulary and Verbal Knowledge and Processing Speed; - Diet assessment: FFQ assessed once at baseline; - Outcome measurement: CD based on MMSE <24 (CI or not, 24 to 30); Funding: Australian Research Council Centre of Excellence in Population Ageing Research
Beydoun, 2022 ^6^; United States; NHANES III Analytic N=4592; Participant characteristics:; - [underlined: Race and/or Ethnicity]:86% NH White; 8% NH Black; 2% Mexican American, 4% Other; - [underlined: SEP]: Education in mean years by Race and/or Ethnicity: ∼12y NH White; ∼9–10y, NH Black; ∼6y Mexican American; ∼9–10y Other; - PIR, mean, by Race and/or Ethnicity: ∼3 NH White; ∼2, NH Black; ∼2 Mexican American; ∼2–3 Other; - SES z-score, mean: 0.51 NH White; −0.27 NH Black, −0.59 Mexican American, 0.07 Other;; - Majority between groups were Married; - [underlined: Selection:] Excluded those without complete/valid diet outcome data | - DP Age(s): 68–72y, mean (60y+ at baseline); - DP(s) examined: Healthy Eating Index (HEI) [Kennedy, 1995]; - DP Components:; - HEI 1995, Positive: Vegetables; Fruit; Grains; Variety. Negative: Meat; Milk; Total Fat, SFA, Cholesterol. Neutral: Sodium; - DP Method(s): Index/Score; Comparisons: Continuous, HEI-1995 | Follow-Up Duration: ∼ 26y, max. Results:; HEI-1995 & Dem (all cause) in non-White vs. NH White, β: −0.052 (SE: 0.052); p=0.32; NH Black v. NH White, ♀ β: 0.001 (SE: 0.063); p=0.99; ♂ β: −0.056 (SE: 0.048); p=0.25; Mexican American v. NH White, ♀ β: 0.0 (SE: 0.068); p=1.00; ♂ β: −0.051 (SE: 0.052); p=0.33; Other v. NH White, ♀ β: 0.054 (SE: 0.07); p=0.42; ♂ β: 0.161 (SE: 0.070); p=0.026; HEI-1995 & Alz in non-White vs. NH White, β: −0.078 (SE: 0.024); p=0.003 NH Black v. NH White, ♀ β: −0.045 (SE: 0.026); p=0.094; ♂ β: −0.159 (SE: 0.101); p=0.12; Mexican American v. NH White, ♀ β: −0.057 (SE: 0.028); p=0.046; ♂ β: −0.175 (SE: 0.106); p=0.11; Other v. NH White, ♀ β: 0.017 (SE: 0.034); p=0.63; ♂ β:−0.042 (SE: 0.112); p=0.71; Summary: Inverse/NS: In non-white v. White participants, HEI-1995+MAR & Cognitive performance; NS/Null: Dem | - Did not account for: Education; - Indirect anlayses of Race and/or Ethnicity as primary exposure, and HEI-1995+MAR as one of many potential mediators to Alz/Dem; - Diet assessment: 24-h recall; - Outcome measurement: Alz and Dem incidence based on linkage of NHANES to NDI and ICD codes; Funding: NIA (NIH)
Boumenna, 2022 ^7^; United States; Boston Puerto Rican Health Study (BPRHS), Analytic N=573; Participant characteristics:; - [underlined: Race and/or Ethnicity]:100% Puerto Rican descent; - [underlined: SEP]: Poverty index under 120%: ∼61–73%; - Job complexity score: ∼40–44 (mean); - <=8th grade education: 47%; - [underlined: Selection:] Excluded those with missing dietary or covariate data | - DP Age(s): 45–75y at baseline; 57.2 y (mean); - DP(s) examined: Mediterranean-Dash Intervention for Neurodegenerative Delay diet (MIND) [Morris, 2015]; - DP Components:; - Positive: Green leafy vegetables; Vegetables; Beans; Berries; Nuts; Whole Grains; Seafood; Poultry; Olive oil; Wine. Negative: Red Meat; Cheese; Pastries and sweets; Butter and stick margarine; Fried/fast food; - DP Method(s): Index/Score; - Comparisons: Categorical, quintiles; Continuous, per 1 pt | Follow-Up Duration: 8 y; Results:; MIND & Global cognitive score (time-varying analyses); Q1, β: 1, ref; Q2, β: 0.005, 95% CI: −0.053, 0.064; Q3, β: 0.006, 95% CI: −0.043, 0.055; Q4, β: 0.047, 95% CI: −0.006, 0.099; Q5, β: 0.093, 95% CI: 0.035, 0.152; p-trend=0.0019; Per pt, β: 0.0213, 95% CI: 0.008, 0.034, p-trend=0.0013; MIND (baseline only) & 8-yr global cognitive score, NS (data NR); Summary: Inverse: time-varying MIND & global cognition (continuous, Q5 vs. Q1); Null: baseline MIND & 8-yr global cognition | - Did not account for: None (all); - ∼70% female; time varying analyses used rather than calculating cognitive change/decline; - Diet assessment: FFQ assessed at baseline, 2-yr, and 5-yr; - Outcome measurement: MMSE; verbal memory; Digit Span forward and backward (attention, working memory); Stroop task; clock drawing; figure copying. Individual scores tranformed to z-scores and composite score computed as mean of individual z-scores; Funding: NIH
Charisis, 2021 ^8^; Greece; Hellenic Longitudinal Investigation of Aging and Diet (HELIAD); Analytic N=1046; Participant characteristics:; - [underlined: Race and/or Ethnicity: NR] (Greek); - [underlined: SEP]: Education: 8.2 (.49)y, mean; - [underlined: Selection:] Excluded those with dementia at baseline or no available dietary info or cognitive F/U | - DP Age(s): 73.1 (5) y; - DP(s) examined: Mediterranean-based Diet Score (MedDietScore) [Panagiotakos 2007]; - DP Components:; - MedDietScore, Positive: Vegetables; Potatoes; Legumes; Fruit; Whole Grains; Fish; Olive Oil. Negative: Red and Processed Meat; Poultry; Full-Fat Dairy; Alcohol; - DP Method(s): Index/Score; Comparisons: Categorical, MedDietScore (quartiles, Q1, HR: 1 or β:0 as REF) | Follow-Up Duration: 3.1 (0.9)y, mean (range: 1.2 to 7.3y); Results:; Global; Q2, β: 0.021, 95% CI: −0.009, 0.050; p=0.169; Q3, β: 0.026, 95% CI: 0.001, 0.051; p=0.049; Q4, β: 0.04, 95% CI: 0.016, 0.063; p=0.001; p-trend=0.001; Executive; Q2, β: 0.035, 95% CI: 0.005, 0.064; p=0.023; Q3, β: 0.033, 95% CI: 0.003, 0.064; p=0.031; Q4, β: 0.053, 95% CI: 0.025, 0.081; p=<0.001; p-trend=0.001; Memory; Q2, β: 0.035, 95% CI: −0.002, 0.072; p=0.061; Q3, β: 0.023, 95% CI: −0.012, 0.059; p=0.198; Q4, β: 0.026, 95% CI: −0.008, 0.060; p=0.136; p-trend=0.24; Language; Q2, β: 0.013, 95% CI: −0.022, 0.048; p=0.466; Q3, β: 0.024, 95% CI: −0.007, 0.055; p=0.132; Q4, β: 0.026, 95% CI: −0.003, 0.055; p=0.077; p-trend=0.059; Visuo-spatial; Q2, β: 0.01, 95% CI: −0.041, 0.061; p=0.705; Q3, β: −0.001, 95% CI: −0.048, 0.047; p=0.972; Q4, β: 0.016, 95% CI: −0.028, 0.060; p=0.478; p-trend=0.573; Attention-speed; Q2, β: 0.022, 95% CI: −0.036, 0.081; p=0.454; Q3, β: 0.038, 95% CI: −0.017, 0.094; p=0.175; Q4, β: 0.058, 95% CI: 0.009, 0.1070; p=0.02; p-trend=0.015; MedDietScore; Q2, HR: 0.84, 95% CI: 0.36, 1.97; p=0.686; Q3, HR: 0.66, 95% CI: 0.29, 1.55; p=0.344; Q4, HR: 0.10, 95% CI: 0.01, 0.78; p=0.029; p-trend=0.023; Summary: Inverse: MedDietScore & Incident Dementia; CD (Impaired Global Cognition; Executive Function; Attention); NS/Null: Memory; Language; Visuospatial | - Did not account for: SEP, Smoking; - n=62 new dementia cases; - Diet assessment: FFQ assessed once at baseline; - Outcome measurement: Dementia based on NINCDS/ADRDA criteria; Individual neuropsychological test scores were used to produce an average domain score for memory, language, attention speed, executive, and visual–spatial functioning; Global cognitive score based on the averages of individual scores; Funding: Alzheimer’s Association; European Social Fund; Ministry of Health and Social Solidarity
Chen, 2017 ^14^; Taiwan; NR; Analytic N=475; Participant characteristics:; - [underlined: Race and/or Ethnicity: NR] (Taiwanese); - [underlined: SEP]: Education, mean ∼13–14y; ≤6 y, ∼5–10%; - [underlined: Selection:] Excluded those using medication for Alzheimer’s disease; those with Hx stroke; missing FFQ data; vegetarians; extreme energy intake; extreme physical activity | - DP Age(s): 73 y (mean); ≥65 y at baseline; - DP(s) examined: “Vegetable” DP; - DP Components:; - “Vegetable” pattern: Positive: dark green vegetables; vegetables with oil; light-colored vegetables; tubers; - DP Method(s): Factor/cluster; - Comparisons: Categorical, tertiles, T1, β and OR: 1 ref; Continuous, per 1 pt | Follow-Up Duration: 2 y; Results:; “Vegetable” DP & CD, NS (data NR); Logical memory-recall I; “Vegetable” DP; T1, β: ref; T2, β: 0.18, 95% CI: 0.03, 0.33; T3, β: 0.16, 95% CI: 0.01, 0.32; p-trend (cont.)=0.005; T1, OR: 1, ref; T2, OR: 0.48, 95% CI: 0.28, 0.83; T3, OR: 0.42, 95% CI: 0.24, 0.74; p-trend (categorical)=0.002; Logical memory-recall II; “Vegetable” DP; T1, β: ref; T2, β: 0.17, 95% CI: 0.01, 0.32; T3, β: 0.21, 95% CI: 0.04, 0.37; p-trend (cont.)=0.01; T1, OR: 1, ref; T2, OR: 0.60, 95% CI: 0.34, 1.06; T3, OR: 0.90, 95% CI: 0.50, 1.60; p-trend (categorical)=0.69; Trail making A; “Vegetable” DP; T1, β: ref; T2, β: 0.04, 95% CI: −0.15, 0.23; T3, β: −0.22, 95% CI: −0.41, −0.02; p-trend (cont.)=0.03; T1, OR: 1, ref; T2, OR: 1.16, 95% CI: 0.69, 1.97; T3, OR: 1.22, 95% CI: 0.71, 2.12; p-trend (categorical)=0.47; Verbal fluency-total score; “Vegetable” DP & Verbal fluency, NS (data NR); Digit span reverse; “Vegetable” DP & Digit span-reverse, NS (data NR); Summary: NS/Null: “Vegetable” DP & CD; Inverse/NS: memory decline (continuous) but NS (categorical); Positive/NS: EF decline (continuous) but NS (categorical) | - Did not account for: SEP, Race and/or Ethnicity, Anthropometry, Alcohol, Smoking; - “Meat” and “Traditional” DPs also examined but did not meet 3+ food group criteria for inclusion: “Meat” pattern: Positive: meat; poultry; roasted meats; “Traditional” pattern: Positive: pickled vegetables; fermented foods; - Diet assessment: FFQ once at baseline; - Outcome measurement: MoCA-T (Montreal Cognitive Assessment-Taiwan version; global cognition); Domain-specific: Wechsler Memory Scale-Third Edition (WMS-III) for logical memory, digit span for attention; Verbal fluency; Trail making tests A & B for executive function; Funding: Ministry of Science and Technology in Taiwan
Chen, 2021 ^12^; Australia; Sydney Memory and Ageing Study (MAS); Analytic N=1037; Participant characteristics:; - [underlined: Race and/or Ethnicity: NR]; - [underlined: SEP]: Mean education: 11.6 y; - [underlined: Selection:] Excluded those with insufficient English to complete assessments; MMSE score of <24 after adjustment for age, education and non-English-speaking background; psychotic symptoms or Dx of schizophrenia or bipolar disorder, multiple sclerosis, motor neuron disease and developmental disability; cancer (excluding prostate or non-malignant skin); other medical or psychological conditions that may prevent assessment | - DP Age(s): 70–90y at baseline; mean 78.8 y; - DP(s) examined: Dietary Guideline Index - Australia (DGI-2013); - DP Components:; - Positive: Vegetables; Fruit; Grain (cereal) foods, mostly whole grain or high fibre; Lean meat and poultry, fish, eggs, nuts and seeds, and legumes/beans; Milk, yogurt, cheese, and/or their alternatives; Fluids (excluding soft drinks, cordial, fruit drinks, flavored milks, or alcoholic beverages). Negative: Discretionary foods; Saturated fat (including whole milk); Unsaturated spreads and oils; Added salt; Added sugars; Alcohol; - DP Method(s): Index/Score; - Comparisons: Categorical, quintiles; Continuous, per 1-pt | Follow-Up Duration: 6 y; Results:; Global cognition (overall); Q1, β: 1, ref; Q2, β: 0.16, 95% CI: −0.05, 0.38, p=0.14; Q3, β: 0.09, 95% CI: −0.05, 0.38, p=0.40; Q4, β: 0.03, 95% CI: −0.20, 0.26, p=0.82; Q5, β: 0.03, 95% CI: −0.19, 0.25, p=0.76; Per 1 pt, β: 0.000, 95% CI: −0.007, 0.007, p=0.95; Global cognition (Δ); Q1, β: 1, ref; Q2, β: 0.03, 95% CI: −0.08, 0.14, p=0.65; Q3, β: 0.06, 95% CI: −0.06, 0.17, p=0.32; Q4, β: 0.03, 95% CI: −0.08, 0.14, p=0.62; Q5, β: 0.04, 95% CI: −0.08, 0.16, p=0.51; Per 1 pt, β: 0.002, 95% CI: −0.002, 0.005, p=0.41; Attention (overall); β: 0.001, 95% CI: −0.006, 0.007, p=0.86; Attention (Δ) β: 0.001, 95% CI: −0.003, 0.004, p=0.75; Language (overall); β: 0.000, 95% CI: −0.007, 0.007, p=0.96; Language (Δ); β: 0.003, 95% CI: −0.000, 0.007, p=0.09; Executive (overall); β: −0.000, 95% CI: −0.007, 0.007, p=0.96; Executive (Δ); β: 0.000, 95% CI: −0.003, 0.004, p=0.80; Visuospatial (overall); β: 6.662, 95% CI: −6.665, 6.668, p=0.40; Visuospatial (Δ); β: −0.001, 95% CI: −0.004, 0.002, p=0.51; Memory (overall); β: −0.001, 95% CI: −0.015, 0.003, p=0.68; Memory (Δ); β: 0.002, 95% CI: −0.007, 0.005, p=0.24; Verbal (overall); β: −0.001, 95% CI: −0.007, 0.005, p=0.67; Verbal (Δ); β: 0.002, 95% CI: −0.001, 0.005, p=0.22; Summary: Null: DGI-2013 & global cognition, all domains (overall & Δ) | - Did not account for: SEP; - Results remained similar (NS) in sensitivity analysis excluding participants in the lowest 10 percentile of cognitive performance at baseline; - Diet assessment: FFQ once at baseline; - Outcome measurement: Global cognition mean of individual domains: attention, language, executive function, visuospatial, memory, verbal; Funding: National Health & Medical Research Council
Chen, 2022 ^13^; Australia; Sydney Memory and Ageing Study (MAS); Analytic N=1037; Participant characteristics:; - [underlined: Race and/or Ethnicity]:White, 98.0%; - Asian, 1.0%; - Other, 1.1%; - [underlined: SEP]: Mean education, 11.6 yrs; - [underlined: Selection:] Excluded those with dementia at baseline/previous Dx of dementia; psychotic Sx or Dx of schizophrenia or bipolar disorder; multiple sclerosis; motor neuron dz; developmental disability; progressive malignancy (active cancer or receiving cancer treatment); implausible energy intake; MMSE score <24; other medical or psychological conditions that may prevent assessment | - DP Age(s): 78.8 y (mean); 70–90 y at baseline; - DP(s) examined: Mediterranean Diet Score (MDS) [Trichopolou 2003]; - Mediterranean-based Diet Score (MedDietScore) [Panagiotakos 2007]; - DASH Score [modified from Fung 2008 by Berendsen 2017]; - DP Components:; - MDS: Positive: Vegetables; Legumes; Fruit, Nuts; Cereals; Fish; MUFA/SFA. Negative: Red and Processed Meat; Dairy Products. Neutral: Alcohol; - MedDietScore: Positive: Vegetables; Potatoes; Legumes; Fruit; Whole Grains; Fish; Olive Oil. Negative: Red and Processed Meat; Poultry; Full-Fat Dairy; Alcohol; - DASH: Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit; Whole Grains; Low-Fat Dairy. Negative: Red and Processed Meat; Total sugar intake; Sodium; - DP Method(s): Index/Score; - Comparisons: Categorical, tertiles; Continuous, per 1 pt | Follow-Up Duration: 6 y; Results:; Overall global cognition (mean over 6 y); MDS; Per 1-pt, β: −0.026, 95% CI: −0.093, 0.041, p-trend= 0.446; T1, β: 1, ref; T2, β: −0.019, 95% CI: −0.186, 0.148, p-trend= 0.821; T3, β: −0.029, 95% CI: −0.219, 0.161, p-trend= 0.764; MedDietScore; Per 1-pt, β: 0.005, 95% CI: −0.018, 0.028, p-trend= 0.690; T1, β: 1, ref; T2, β: 0.047, 95% CI: −0.210, 0.303, p-trend= 0.722; T3, β: 0.077, 95% CI: −0.188, 0.343, p-trend= 0.568; DASH; Per 1-pt, β: 0.008, 95% CI: −0.019, 0.035, p-trend= 0.570; T1, β: 1, ref; T2, β: 0.091, 95% CI: −0.155, 0.337, p-trend= 0.467; T3, β: 0.029, 95% CI: −0.249, 0.308, p-trend= 0.835; Decline global cognition (slope over 6 y); MDS; Per 1-pt, β: 0.010, 95% CI: −0.012, 0.327, p-trend= 0.374; T1, β: 1, ref; T2, β: 0.049, 95% CI: −0.035, 0.133, p-trend= 0.254; T3, β: 0.024, 95% CI: −0.072, 0.121, p-trend= 0.621; MedDietScore; Per 1-pt, β: 0.001, 95% CI: −0.006, 0.008, p-trend= 0.791; T1, β: 1, ref; T2, β: 0.037, 95% CI: −0.045, 0.118, p-trend= 0.376; T3, β: 0.011, 95% CI: −0.075, 0.097, p-trend= 0.807; DASH; Per 1-pt, β: −0.001, 95% CI: −0.010, 0.008, p-trend= 0.781; T1, β: 1, ref; T2, β: −0.015, 95% CI: −0.100, 0.069, p-trend= 0.727; T3, β: −0.010, 95% CI: −0.099, 0.078, p-trend= 0.817; Summary: Null: MDS, MedDietScore, DASH & overall cognition; Null: MDS, MedDietScore, DASH & cognitive decline | - Did not account for: SEP, Alcohol (DASH score only); - Main analyses included imputed data, sensitivity analyses including only those with complete data (n=484) yielded largely similar results; - Diet assessment: FFQ once at baseline; - Outcome measurement: Cognitive function at baseline, 2-yr, 4-yr, and 6-yr using face-to-face assessments: Attention/processing speed (Digit Symbol-Coding, Trail Making Test A); Verbal memory (Logical Memory Story A delayed recall, Rey Auditory Verbal Learning Test of total learning, immediate and delayed recall); Global memory (verbal memory measures, Benton Visual Retention Test recognition); Language tests (Boston Naming Test, Semantic Fluency (Animals)); Visuospatial cognition (Block Design test); Executive function (Controlled Oral Word Association Test, Trail Making Test B); Funding: National Health and Medical Research Council Australia
Chen, 2023 ^10^; Finland; Cardiovascular Risk in Young Finns Study (YFS); Analytic N=790; Participant characteristics:; - [underlined: Race and/or Ethnicity: NR] (100% Finnish); - [underlined: SEP]: SES from family income, parent education and employment, mean (SD): 0.01 (0.6); - [underlined: Selection:] Excluded those who had missing dietary, dementia, or risk factor data | - DP Age(s): 11y, mean (3–18y at baseline); - DP(s) examined: Youth DPs: “Traditional Finnish” 1980; “High-carbohydrate” 1980; “Vegetables and dairy products 1980”; Adult DPs: “Traditional Finnish and high-carbohydrate” 2011; “Red meat” 2011; “Healthy” 2011; - DP Components:; - “Traditional Finnish” 1980: high intake of butter, rye, potatoes, coffee, milk, and sausages and a low intake of fruit and berries;; - “High-carbohydrate” 1980: high intake of margarine and oils, wheat, sugar, eggs, milk, other meat, other grain products, potatoes, and fruit and berries;; - “Vegetables and dairy products 1980”: high intake of vegetables, cheese, and other dairy products.; - “Traditional Finnish and high-carbohydrate” 2011: high intake of grain products, potatoes, butter, sugar, and margarine and oils;; - “Red meat” 2011: high intake of pork, eggs, sausages, offal, other meat, and fish;; - “Healthy” 2011: high intake of vegetables, legumes and nuts, fish, fruit and berries, cheese, and tea; - DP Method(s): Factor/Cluster; Comparisons: Continuous, per SD of each DP | Follow-Up Duration: 31y, mean; Results:; Each DP & Episodic memory & associative learning, β (95% CI); Traditional Finnish; long-term, β: −0.062 (−0.142, 0.018); youth, β: −0.067 (−0.149, 0.016); adult, β: −0.011 (−0.093, 0.071); High-carbohydrate; long-term, β: −0.041 (−0.115, 0.032); youth, β: 0.023 (−0.053, 0.098); adult, β: −0.078 (−0.154, −0.001); Vegetables and dairy products; long-term, β: 0.111 (0.035, 0.186); youth, β: 0.094 (0.019, 0.169); adult, β: 0.049 (−0.026, 0.125); Traditional Finnish and high-carbohydrate; long-term, β:−0.052 (−0.123, 0.020); youth, β: 0.050 (−0.024, 0.124); adult, β:−0.121 (−0.197, −0.045); Healthy; long-term, β: 0.080 (0.001, 0.158); youth, β: 0.110 (0.035, 0.185); adult, β: −0.018 (−0.103, 0.066); Red meat; long-term, β: 0.020 (−0.054, 0.093); youth, β: −0.018 (−0.090, 0.053); adult, β: 0.046 (−0.030, 0.122); Each DP & Working memory & problem solving, β (95% CI); Traditional Finnish; long-term, β: −0.097 (−0.171, −0.022); youth, β: −0.085 (−0.162, −0.007); adult, β: −0.037 (−0.113, 0.039); High-carbohydrate long-term, β: −0.006 (−0.074, 0.062); youth, β: 0.065 (−0.004, 0.135); adult, β: −0.072 (−0.144, −0.001); Vegetables and dairy products; long-term, β: 0.034 (−0.036, 0.104); youth, β: −0.003 (−6.674, 6.668); adult, β: 0.046 (−0.025, 0.117); Traditional Finnish and high-carbohydrate; long-term, β: −0.049 (−0.116, 0.018); youth, β: 0.045 (−0.024, 0.114); adult, β: −0.115 (−0.187, −0.043); Healthy; long-term, β: −0.032 (−0.106, 0.042); youth, β: 0.026 (−0.045, 0.098); adult, β: −0.075 (−0.156, 0.005); Red meat; long-term, β: −0.018 (−0.087, 0.051); youth, β: −0.068 (−0.136, 0.0001); adult, β: 0.049 (−0.024, 0.121); Each DP & Reaction & Movement Time (RTI), β (95% CI); Traditional Finnish; long-term, β: −0.059 (−0.141, 0.023); youth, β: −0.038 (−0.123, 0.047); adult, β: −0.035 (−0.120, 0.049); High-carbohydrate; long-term, β: −0.046 (−0.121, 0.030); youth, β: −0.007 (−0.084, 0.070); adult, β: −0.055 (−0.133, 0.023); Vegetables and dairy products; long-term, β: 0.022 (−0.055, 0.100); youth, β: 0.021 (−0.056, 0.098); adult, β: 0.008 (−0.069, 0.086); Traditional Finnish and high-carbohydrate; long-term, β: −0.044 (0.117, 0.030); youth, β: −0.031 (−1.07, 0.045); adult, β: −0.030 (0.108, 0.048); Healthy; long-term, β: −0.006 (−0.088, 0.076); youth, β: 0.039 (−0.039, 0.116); adult, β: −0.054 (−0.141, 0.034); Red meat; long-term, β: −0.034 (−0.110, 0.042); youth, β: −0.052 (−0.128, 0.024); adult, β: 0.008 (−0.070, 0.086); Each DP & Visual processing/attention (RVP), β (95% CI); Traditional Finnish; long-term, β: −0.064 (−0.140, 0.012); youth, β: −0.055 (−0.134, 0.024); adult, β: −0.026 (−0.103, 0.052); High-carbohydrate; long-term, β: −0.079 (−0.148, −0.010); youth, β: −0.009 (−0.080, 0.062); adult, β: −0.099 (−0.172, −0.027); Vegetables and dairy products; long-term, β: 0.073 (0.001, 0.144); youth, β: 0.040 (−0.032, 0.112); adult, β: 0.053 (−0.018, 0.125); Traditional Finnish and high-carbohydrate; long-term, β: −0.117 (−0.185, −0.049); youth, β: −0.005 (−0.074, 0.065); adult, β: −0.161 (−0.234, −0.089); Healthy; long-term, β: −0.054 (−0.131, 0.022); youth, β: 0.001 (−0.073, 0.074); adult, β: −0.075 (−0.158, 0.007); Red meat; long-term, β: 0.079 (0.007, 0.150); youth, β: −0.002 (−0.073, 0.069); adult, β: 0.104 (0.031, 0.178); Summary: Inverse: Traditional Finnish in youth and long-term & working memory/problem solving; NS/Null all other analyses; Inverse: High Carbohydrate DP in adulthood & episodic memory/associative learning, working memory/problem solving; NS/Null: all other analyses; Positive: Vegetables and Dairy DP in youth and long-term & episodic memory/associative learning; in long term & visual processing/attention; NS/Null: all other analyses; Positive: “Healthy” DP in youth and long-term & episodic memory/associative learning and visual processing/attention; NS/Null: all other analyses; Inverse: High-carbohydrate DP in adulthood & episodic memory/associative learning and and visual processing/attention; long-term & visual processing/attention; NS/Null: all other analyses; Inverse: Traditional Finnish and High Carbohydrate DP in adulthood & episodic memory/associative learning; NS/Null: all other analyses; Positive: Red Meat DP in adulthood and long-term & visual processing/attention; NS/Null: all other analyses | - Did not account for: Alcohol; Race and/or Ethnicity (Finnish); - Indirectly examining CD via cognitive function; - Diet assessment: 48h-recall (50% of participants at basline) or FFQ (100% at repeat visits); - Outcome measurement: CD based on computerized cognitive battery of tests (for episodic memory/learning; working memory/problem solving; reaction/movement time; visual processing and attention); Funding: Academy of Finland; Social Insurance Institution of Finland; Competitive State Research Financing of the Expert Responsibility area of Kuopio, Tampere and Turku University Hospitals; Juho Vainio Foundation; Paavo Nurmi Foundation; Finnish Foundation for Cardiovascular Research; Finnish Cultural Foundation; The Sigrid Juselius Foundation; Tampere Tuberculosis Foundation; Emil Aaltonen Foundation; Yrjo Jahnsson Foundation; Signe and Ane Gyllenberg Foundation; Diabetes Research Foundation of Finnish Diabetes Association; EU Horizon 2020; European Research Council; Tampere University Hospital Supporting Foundation
Chen, 2023 ^11^; Taiwan; Taiwan Initiative for Geriatric Epidemiological Research (TIGER); Analytic N=436; Participant characteristics:; - [underlined: Race and/or Ethnicity]:“100% ethnically Chinese”; - SEP: NR; - [underlined: Selection:] Excluded those with Hx stroke, brain tumor, head traums; dementia at baseline; use of medications to treat Alzheimer’s disease; incomplete FFQ data; extreme energy intakes or reported physical activity; vegetarians excluded | - DP Age(s): 71.6 y, mean (≥65 y); - DP(s) examined: modified Alternative Healthy Eating Index (mAHEI) [Dehghan, 2012]; - DP Components:; - mAHEI, Positive: Vegetables; Fruits; Soy Protein; Whole Grains; Fish: Meat: Egg ratio; Negative: Fried foods; Neutral: Alcohol; - DP Method(s): Index/Score; Comparisons: Trajectory: Deteriorating mAHEI; Improving mAHEI; Stable-High mAHEI | Follow-Up Duration: 6 y; Results:; Deteriorating vs. Stable-High mAHEI & global CD (MoCA-T), β: −0.00, 95% CI: −1.00, 1.00; Memory, β: −0.15, 95% CI: −0.55, 0.24; Theme Recall, β: −0.14, 95% CI: −0.57, 0.29; Free Recall, β: −0.08, 95% CI: −0.49, 0.33; Delayed Theme Recall, β: −0.24, 95% CI: −0.68, 0.20; Delayed Free Recall, β: −0.15, 95% CI: −0.59, 0.29; EFx, β: −0.07, 95% CI: −0.35, 0.21; TMT-A, β: −0.05, 95% CI: −0.31, 0.21; TMT-B, β: −0.08, 95% CI: −0.46, 0.30; Attn, β: −0.03, 95% CI: −0.32, 0.27; Digit Span-F, β: 0.00, 95% CI: −0.37, 0.37; Digit Span-B, β: −0.06, 95% CI: −0.40, 0.28; VF, β: −0.30, 95% CI: −0.63, 0.02; Improving vs. Stable-High mAHEI & global CD (MoCA-T), β: −0.43, 95% CI: −1.07, 0.20; Memory, β: −0.40, 95% CI: −0.66, −0.15; p<0.01; Immediate Theme Recall, β: −0.32, 95% CI: −0.60, −0.05; p<0.05; Immediate Free Recall, β: −0.43, 95% CI: −0.69, −0.17; p<0.01; Delayed Theme Recall, β: −0.41, 95% CI: −0.69, −0.13; p<0.01; Delayed Free Recall, β: −0.45, 95% CI: −0.73, −0.17; p<0.01; EFx, β: 0.01, 95% CI: −0.17, 0.18; TMT-A, β: 0.01, 95% CI: −0.16, 0.18; TMT-B, β: −0.00, 95% CI: −0.24, 0.24; Attn, β: 0.04, 95% CI: −0.14, 0.23; Digit Span-F, β: 0.11, 95% CI: −0.13, 0.34; Digit Span-B, β: −0.02, 95% CI: −0.23, 0.20; VF, β: −0.07, 95% CI: −0.28, 0.14; Summary: NS/Positive: Stable-High mAHEI (v. Deterioriating) & Global MoCA-T; Memory; Recall; EFx; TMT; Attn.; Digit Span; VF); Positive: Stable-High mAHEI (v. Improving) & Memory and Recall performance (NS: global MoCA-T; EFx; TMT; Attn.; Digit Span; VF) | - Did not account for: SEP, Smoking; - Diet assessment: FFQ assessed at baseline, 4th, and 6th year F/U; Nuts excluded from index/score due to low consumption; - Outcome measurement: Global cognition: MoCA-T (Montreal Cognitive Assessment—Taiwanese version) (once at baseline and once at f/u); - Domain-specific: Wechsler Memory Scale-Third edition (WMS-III) for logical memory and attention; TMT-A & B for EF; verbal fluency included naming fish, vegetables, and fruit within 1 minute; Funding: Ministry of Science and Technology, Taiwan
Chen, 2023 ^9^; United States, United Kingdom; Whitehall II study (WII - UK), Health and Retirement Study (HRS - US), Framingham Heart Study Offspring cohort (FOS - US); Analytic N=18136 (pooled); WII: 8358; HRS: 6758; FOS: 3020; Participant characteristics:; - [underlined: Race and/or Ethnicity]:WII: 90.9% White; Other n/a; - HRS: 70.5% White; 15.4% Black; 10.8% Hispanic; 3.3% Other; - FOS: NR; - [underlined: SEP]: Education, mean 13.1–15.3y; - Low occupation position (WII): 15.1%; - HH Income quartiles (HRS & FOS): 1st, 20.3–24.6; 2nd, 23.4–24.5; 3rd, 24.2–28.1; 4th, 26.7–28.2; - [underlined: Selection:] Excluded those with dementia at baseline or within 2 years of follow-up;; - WII included civil workers aged 35–55y in 1985; HRS included ages 50y+; FOS included children and spouses of the Framingham Heart Study | - DP Age(s): ∼64 y at baseline; - 62.2 y (WII); 66.5 (HRS); 64.2 (FOS); - DP(s) examined: Mediterranean-Dash Intervention for Neurodegenerative Delay diet (MIND) [Morris, 2015]; - DP Components:; - MIND: Positive: Green leafy vegetables; Vegetables; Beans; Berries; Nuts; Whole Grains; Seafood; Poultry; Olive oil; Wine. Negative: Red Meat; Cheese; Pastries and sweets; Butter and stick margarine; Fried/fast food; - DP Method(s): Index/Score; - Comparisons: Categorical, tertiles (T1, HR: 1, ref); Continuous, per 3-pt increase | Follow-Up Duration: 5.0–12.9 y; HRS: 5.0y; FOS: 10.7y; WII: 12.9y; Results:; MIND & Dem (95% CI); Pooled WHII, HRS, FOS; T1, HR: 1, ref; T2, HR: 0.97 (0.81, 1.15); T3, HR: 0.81 (0.67, 0.98); Per 3-pt, HR: 0.83 (0.72, 0.95); p-trend=0.01; WII, HR (95% CI); T1, HR: 1, ref; T2, HR: 1.03 (0.73, 1.45); T3, HR: 0.96 (0.66, 1.38); Per 3-pt, HR: 0.97 (0.72, 1.30); p-trend=0.83; HRS, HR (95% CI); T1, HR: 1, ref; T2, HR: 0.95 (0.73, 1.25); T3, HR: 0.83 (0.63, 1.09); Per 3-pt, HR: 0.82 (0.68, 0.99); p-trend=0.04; FOS, HR (95% CI); T1, HR: 1, ref; T2, HR: 0.96 (0.70, 1.33); T3, HR: 0.69 (0.48, 0.99); Per 3-pt, HR: 0.76 (0.57, 1.00); p-trend=0.04; Summary: Inverse: MIND & Dem (Pooled, HRS, FOS); Null: MIND & Dem (WII) | - Did not account for: Race and/or Ethnicity (“Western” population of similar cultural and ethnic background); - In subgroup analyses, MIND diet not associated with dementia risk among smokers but was inversely associated among non-smokers; - For HRS: “did not directly assess the status of dementia” but Langa-Weir Classification strategy “showed both high specificity a; - Diet assessment: FFQ (once at baseline for HRS); - Outcome measurement: WII: medical record linked to obtain dementia incidence. HRS: Langa-Weir Classification strategy-defined dementia case if participant had a poor objective performance (<=6 out of 27) in self-respondent interview or had a high score in cognitive disability (>=6 out of 11) assessed by a proxy respondent. FOS: a dementia review panel consisting of a neurologist and a neuropsychologist reviewed every possible case of dementia.; Funding: NR
Chou, 2019 ^15^; Taiwan; Taiwan Initiative for Geriatric Epidemiological Research (TIGER); Analytic N=436; Participant characteristics:; - [underlined: Race and/or Ethnicity: NR] (100% Taiwanese); - [underlined: SEP]: Relatively high education & income:; - Mean education, 14.0 yrs; - Annual disposable income (converted from TWD to USD):; - <$9,252.00, 16%; - $9,252.00–24,672.00, 26%; - $24,672.00–30,840.00, 15%; - $>30,840.00, 43%; - [underlined: Selection:] Excluded those with Hx stroke, brain tumor, head traums; dementia at baseline; use of medications to treat Alzheimer’s disease; incomplete FFQ data; extreme energy intakes or reported physical activity; vegetarians excluded | - DP Age(s): 72.5 y, mean (≥65 y); - DP(s) examined: modified Alternative Healthy Eating Index (mAHEI) [Dehghan, 2012]; - DP Components:; - mAHEI, Positive: Vegetables; Fruits; Soy Protein; Whole Grains; Fish: Meat: Egg ratio; Negative: Fried foods; Neutral: Alcohol; - DP Method(s): Index/Score; Comparisons: Categorical, tertiles | Follow-Up Duration: 2 y; Results:; Global (MoCA-T); T1, OR: 1, ref; T2, OR: 0.87, 95% CI: 0.50, 1.51; T3, OR: 0.54, 95% CI: 0.31, 0.95; p-trend=0.03; Logical memory; T1, OR: 1, ref; T2, OR: 1.13, 95% CI: 0.62, 2.07; T3, OR: 0.76, 95% CI: 0.42, 1.38; p-trend=0.38; Verbal fluency; T1, OR: 1, ref; T2, OR: 1.18, 95% CI: 0.69, 2.03; T3, OR: 0.94, 95% CI: 0.53, 1.64; p-trend=0.84; Executive function; T1, OR: 1, ref; T2, OR: 1.27, 95% CI: 0.75, 2.13; T3, OR: 1.12, 95% CI: 0.65, 1.91; p-trend=0.68; Attention; T1, OR: 1, ref; T2, OR: 1.03, 95% CI: 0.60, 1.76; T3, OR: 0.56, 95% CI: 0.32, 0.99; p-trend=0.049; Summary: Inverse: mAHEI & CD, attention decline; NS: logical memory, verbal fluency, EFx | - Did not account for: SEP (except global, memory), Physical Activity, Anthropometry (except verbal fluency), Race and/or Ethnicity (100% Taiwanese), Smoking; - “our participants were recruited from a senior health checkup program in Taipei City, who tended to have higher education level, annual disposable income, and be more healthconscious than the general population”; - Diet assessment: FFQ assessed once at baseline; Nuts excluded from index/score due to low consumption; - Outcome measurement: Global cognition: MoCA-T (Montreal Cognitive Assessment—Taiwanese version) (once at baseline and once at f/u); - Domain-specific: Wechsler Memory Scale-Third edition (WMS-III) for logical memory and attention; TMT-A & B for EF; verbal fluency included naming fish, vegetables, and fruit within 1 minute; Funding: Ministry of Science and Technology, Taiwan
Corley & Deary, 2021 ^16^; Scotland; Lothian Birth Cohort 1936 (LBC1936); Analytic N=364; Participant characteristics:; - [underlined: Race and/or Ethnicity: NR]; - [underlined: SEP]: Mean education, ∼10.5–11 years; - Married, ∼70–75%; - SES (professional), ∼70–90% (higher in those with higher mediterranean, lower traditional adherence); - [underlined: Selection:] Excluded those with missing/incomplete FFQ; extreme energy intake; Dementia at baseline | - DP Age(s): 69.5 y (mean) at baseline; - DP(s) examined: Mediterranean Diet Score (MDS) [Trichopolou 2003]; - DP Components:; - “Mediterranean-style” PCA: Positive: Vegetables (leeks or courgettes, tomatoes, broccoli, spinach, other salad vegetables); Fish; Legumes; Olive oil; Salad dressing; Poultry; Pasta; Rice; Water; Tomato-based sauces; - “Traditional” PCA: Positive: Meat; Processed meats (such as pies, pasties and sausage rolls); Mashed potatoes; Tinned vegetables; Peas or beans; Carrots; Baked beans; Bottled sauces’ Custard or other sweet sauces; Milk-based puddings. Negative: filter, espresso and cappuccino coffee; - MDS: Positive: Vegetables; Legumes; Fruit, Nuts; Cereals; Fish; MUFA/SFA. Negative: Red and Processed Meat; Dairy Products. Neutral: Alcohol; - DP Method(s): Factor/Cluster, Index/Score; Comparisons: Continuous | Follow-Up Duration: 12.5 y (mean); Results:; ΔGlobal cognition; Mediterranean, Est. −0.002, SE: 0.001, p-trend= 0.17; Traditional, Est. 0.000, SE: 0.001, p-trend= 0.88; MDS, Est. 0.000, SE: 0.001, p-trend= 0.49; ΔVisuospatial ability; Mediterranean, Est. −0.000, SE: 0.002, p-trend= 0.87; Traditional, Est. −0.003, SE: 0.002, p-trend= 0.14; MDS, Est. 0.001, SE: 0.001, p-trend= 0.40; ΔProcessing speed; Mediterranean, Est. −0.003, SE: 0.002, p-trend= 0.09; Traditional, Est. 0.001, SE: 0.002, p-trend= 0.93; MDS, Est. 0.000, SE: 0.001, p-trend= 0.71; ΔMemory; Mediterranean, Est. −0.001, SE: 0.002, p-trend= 0.59; Traditional, Est. 0.000, SE: 0.003, p-trend= 0.92; MDS, Est. 0.000, SE: 0.001, p-trend= 0.82; ΔVerbal ability; Mediterranean, Est. −0.003, SE: 0.001, p-trend= 0.008; Traditional, Est. −0.001, SE: 0.001, p-trend= 0.29; MDS, Est. 0.001, SE: 0.001, p-trend= 0.63; Summary: Inverse: Mediterranean & verbal ability; NS/Null: Mediterranean & Global cognition, visuospatial ability, processing speed, memory; NS/Null: Traditional & Global cognition, visuospatial ability, processing speed, memory, verbal ability; NS/Null: MDS & Global cognition, visuospatial ability, processing speed, memory, verbal ability | - Did not account for: Education, Anthropometry, Race and/or Ethnicity, Alcohol (PCA patterns); - Slope (i.e., cognitive change/decline) models included only those with cognitive data through age 82. Results similar when including participants with dementia (N=882); - Diet assessment: FFQ once at baseline; PCA previously derived in Mottus et al.; - Outcome measurement: Cognitive domains assessed every 3 years from age 73–82y: Visuospatial ability (Matrix Reasoning (WAIS-III), Block Design (WAISIII), Spatial Span (WMS-III), average of Forwards and Backwards); Processing speed (Digit Symbol (WAISIII), Symbol Search (WAIS-III), Choice Reaction Time, Inspection Time); Memory (Logical Memory Immediate and Delayed Recall (WMSIII), Verbal Pairs Immediate and Delayed Recall (WMSIII), Digits Backwards (WAIS-III)); Verbal ability (National Adult Reading Test, Wechsler Test of Adult Reading, and Verbal Fluency).; Funding: Age UK (Disconnected Mind project); UK Medical Research Council; NIH
Cornelis, 2023 ^17^; United Kingdom; UK Biobank Analytic N=120,661 (CD); 78663 (Dem); Participant characteristics:; - [underlined: Race and/or Ethnicity]:White, ≥96%; - South Asian, ∼1%; - Black, ∼0.8%; - Chinese, ∼0.2%; - Other/Unknown, ∼1.4%; - [underlined: SEP]: Townsend deprivation index, ∼ −1.6; - Household income ≥52,000 euro, ∼30%; - College/University degree, ∼40–50%; - Currently employed, ∼60%; - [underlined: Selection:] Included those who recruited in 2009–10, with at least two FFQs | - DP Age(s): 37–73 y at baseline; incident dementia 55+ only; mean age ∼57–58; - DP(s) examined: Mediterranean-Dash Intervention for Neurodegenerative Delay diet (MIND) [Morris, 2015]; - adjusted Alternative HEI (AHEI)-2010 [Chiuve 2012], for UKB cohort used oily fish in lieu of n-3; - DP Components:; - MIND: Positive: Green leafy vegetables; Vegetables; Beans; Berries; Nuts; Whole Grains; Seafood; Poultry; Olive oil; Wine. Negative: Red Meat; Cheese; Pastries and sweets; Butter and stick margarine; Fried/fast food; - AHEI-2010: Positive: Vegetables (not potatoes, French fries); Fruit; Legumes and Nuts; Whole Grains; Oily Fish (in lieu of n-3 for UKB cohort). Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Trans FA; Sodium. Neutral: Alcohol; - DP Method(s): Index/Score; - Comparisons: Categorical, tertiles; Continuous, per 1 pt & per SD | Follow-Up Duration: 10.5 y; Results:; MIND; Fluid Intelligence (higher score = better perfomance); T1, β: 1, ref; T2, β: −0.03, 95% CI: −0.07, 0.007, p-trend=0.12; T3, β: −0.14, 95% CI: −0.18, −0.10, p-trend<0.0001; per 1-pt, β: −0.04, 95% CI: −0.05, −0.03; per-SD, β: −0.07, 95% CI: −0.09, −0.06 p-trend (linear)<0.0001; Reaction time (lower score = better performance); T1, β: 1, ref; T2, β: −0.47, 95% CI: −1.85, 0.91, p-trend=0.51; T3, β: 0.66, 95% CI: −0.70, 2.02, p-trend=0.34; per 1-pt, β: 0.33, 95% CI: 0.03, 0.62; per-SD, β: 0.63, 95% CI: 0.06, 1.21; p-trend (linear)=0.03; Pairs matching (lower score = better performance); T1, β: 1, ref; T2, β: 0.01, 95% CI: 0.001, 0.02, p-trend=0.03; T3, β: 0.03, 95% CI: 0.02, 0.04, p-trend<0.0001; per 1-pt, β: 0.008, 95% CI: 0.006, 0.01; per-SD, β: 0.02, 95% CI: 0.01, 0.02; p-trend (linear)<0.0001; Symbol digital substitution (higher score = better performance); T1, β: 1, ref; T2, β: −0.07, 95% CI: −0.15, 0.02, p-trend=0.16; T3, β: −0.25, 95% CI: −0.33, −0.16, p-trend<0.0001; per 1-pt, β: −0.07, 95% CI: −0.09, −0.05; per-SD, β: −0.14, 95% CI: −0.17, −0.10 p-trend (linear)<0.0001; Trail A (lower score = better performance); T1, β: 1, ref; T2, β: 0.005, 95% CI: −0.001, 0.01. p-trend=0.10; T3, β: 0.01, 95% CI: 0.007, 0.02, p-trend<0.0001; per 1-pt, β: 0.003, 95% CI: 0.002, 0.004; per-SD, β: 0.006, 95% CI: 0.003, 0.008; p-trend (linear)<0.0001; Trail B (lower score = better performance); T1, β: 1, ref; T2, β: 0.01, 95% CI: 0.005, 0.02, p-trend=0.0002; T3, β: 0.02, 95% CI: 0.02, 0.03, p-trend<0.0001; per 1-pt, β: 0.006, 95% CI: 0.005, 0.008; per-SD, β: 0.012, 95% CI: 0.010, 0.015; p-trend (linear)<0.0001; Prospective memory (higher score = better performance); T1, β: 1, ref; T2, β: 1.01, 95% CI: 0.95, 1.07, p-trend=0.78; T3, β: 0.95, 95% CI: 0.90, 1.01, p-trend=0.11; per 1-pt, β: 0.98, 95% CI: 0.97, 0.99; per-SD, β: 0.96, 95% CI: 0.94, 0.99; p-trend (linear)=0.004; AHEI-2010; Fluid intelligence (higher score = better performance); T1, β: 1, ref; T2, β: −0.05, 95% CI: −0.09, −0.008, p-trend=0.02; T3, β: −0.17, 95% CI: −0.21, −0.13, p-trend<0.0001; per 1-pt, β: −0.006, 95% CI: −0.007, −0.004; per-SD, β: −0.08, 95% CI: −0.09, −0.06 p-trend (linear)<0.0001; Reaction time (lower score = better performance); T1, β: 1, ref; T2, β: 1.23, 95% CI: −0.12, 2.57, p-trend=0.07; T3, β: 2.77, 95% CI: 1.37, 4.16, p-trend<0.0001; per 1-pt, β: 0.10, 95% CI: 0.06, 0.14; per-SD, β: 1.41, 95% CI: 0.83, 1.99; p-trend (linear)<0.0001; Pairs matching (lower score = better performance); T1, β: 1, ref; T2, β: 0.03, 95% CI: 0.02, 0.04, p-trend<0.0001; T3, β: 0.04, 95% CI: 0.03, 0.05, p-trend<0.0001; per 1-pt, β: 0.001, 95% CI: 0.0011, 0.0017; per-SD, β: 0.019, 95% CI: 0.016, 0.023; p-trend (linear)<0.0001; Symbol digital substitution (higher score = better performance); T1, β: 1, ref; T2, β: −0.19, 95% CI: −0.27, −0.11, p-trend<0.0001; T3, β: −0.40, 95% CI: −0.49, −0.32, p-trend<0.0001; per 1-pt, β: −0.013, 95% CI: −0.016, −0.011; per-SD, β: −0.18, 95% CI: −0.22, −0.15; p-trend (linear)<0.0001; Trail A (lower score = better performance); T1, β: 1, ref; T2, β: 0.009, 95% CI: 0.003, 0.01, p-trend=0.002; T3, β: 0.02, 95% CI: 0.01, 0.03, p-trend<0.0001; per 1-pt, β: 0.0006, 95% CI: 0.0004, 0.0008; per-SD, β: 0.008, 95% CI: 0.006, 0.01; p-trend (linear)<0.0001; Trail B (lower score = better performance); T1, β: 1, ref; T2, β: 0.015, 95% CI: 0.009, 0.021, p-trend<0.0001; T3, β: 0.034, 95% CI: 0.028, 0.039, p-trend<0.0001; per 1-pt, β: 0.0011, 95% CI: 0.0009, 0.0012; per-SD, β: 0.015, 95% CI: 0.012, 0.017; p-trend (linear)<0.0001; Prospective memory (higher score = better performance); T1, β: 1, ref; T2, β: 0.89, 95% CI: 0.84, 0.95, p-trend=0.0003; T3, β: 0.90, 95% CI: 0.85, 0.96, p-trend=0.002; per 1-pt, β: 1.00, 95% CI: 0.99, 1.00; per-SD, β: 0.95, 95% CI: 0.92, 0.97; p-trend (linear)<0.0001; All-cause dementia; MIND; T1, β: 1, ref; T2, β: 1.06, 95 %CI: 0.90, 1.24, p-trend=0.51; T3, β: 0.90, 95% CI: 0.74, 1.09, p-trend=0.27; Per 1-pt, β: 0.99, 95% CI: 0.95, 1.03; Per-SD, β: 0.97, 95% CI: 0.90, 1.05; p-trend (linear)=0.48; AHEI-2010; T1, β: 1, ref; T2, β: 0.93, 95% CI: 0.78, 1.10, p-trend=0.38; T3, β: 0.89, 95% CI: 0.75, 1.06, p-trend=0.20; Per 1-pt, β: 1.00, 95% CI: 0.99, 1.00; Per-SD, β: 0.94, 95% CI: 0.87, 1.01; p-trend (linear)=0.10; MIND; T1, β: 1, ref; T2, β: 1.00, 95% CI: 0.78, 1.30, p-trend=0.98; T3, β: 0.96, 95% CI: 0.72, 1.28, p-trend=0.76; Per 1-pt, β: 1.01, 95% CI: 0.95, 1.07; Per-SD, β: 1.02, 95% CI: 0.91, 1.14; p-trend (linear)=0.76; AHEI-2010; T1, β: 1, ref; T2, β: 0.94, 95% CI: 0.72, 1.23, p-trend=0.66; T3, β: 0.99, 95% CI: 0.75, 1.29, p-trend=0.91; Per 1-pt, β: 1.00, 95% CI: 0.99, 1.01; Per-SD, β: 1.01, 95% CI: 0.90, 1.14; p-trend (linear)=0.82; Summary: Positive: MIND score & (worse) cognition (Fluid intelligence, reaction time (linear), pairs matching, symbol digital substitution, Trail A, Trail B, prospective memory (linear)); NS/Inverse: MIND & All-cause Dementia; NS/Null: Alzheimer’s Dementia; cognitive function (reaction time (tertiles), prospective memory (tertiles)); Positive: AHEI-2010 & (worse) cognitive function (Fluid intelligence, reaction time, pairs matching, symbol digital substitution, Trail A, Trail B, prospective memory); NS/Inverse: AHEI-2010 & All-cause Dementia, NS/Null: Alzheimer’s Dementia | - Did not account for: None (all); - No composite measure of cognitive function; no adjustment for multiple testing; - Diet assessment: At least two WebQ’s (24-hr recalls), each asssessed ∼3–4 months apart; - Outcome measurement: CD: Computerized cogntiive function tests developed for UKB: prospective memory (PM), fluid intelligence (FI, verbal-numerical reasoning), pairs matching (Pairs, visual memory) and reaction time (RT); - Dem: all cause dementia derived from hospital admission and death records; ICD-10 codes; further classified as Alzheimer’s when possible; Funding: NIH
D’Amico, 2020 ^18^; Canada; Quebec Longitudinal Study on Nutrition and Successful Aging (NuAge); Analytic N=1045; Participant characteristics:; - [underlined: Race and/or Ethnicity]:987% Caucasian; - [underlined: SEP]: Education <12 years, 50.1%; - [underlined: Selection:] Excluded those with cerebral vascular Dz, Parkinson’s Dz, epilepsy, or muscular dystrophy; those with extreme energy intakes | - DP Age(s): 74.2 y (mean); 67–84 y at baseline; - DP(s) examined: n/a; - DP Components:; - “Prudent” ♂: Positive: fruits, vegetables, fatty fish, legumes, nuts and seeds, rice and rice dishes, poultry, high-fiber cereals, tofu, and lower-fat dairy products; - “Western” ♂: Positive: red and processed meats, pork, potatoes, white bread, fried foods, butter, baked goods, sugary foods and drinks, high-fat dairy products, eggs and egg dishes, and salty snacks; - “Prudent” ♀: Positive: fruits, vegetables, fatty fish, poultry, rice and rice dishes, legumes, eggs and egg dishes, nuts and seeds, tofu, low-fat dairy products, and cheese; - “Western” ♀: Positive: red and processed meats, pork, white bread, potatoes, fried foods, butter, pasta, baked goods, sugary foods and drinks, high-fat dairy products, and salty snacks; - DP Method(s): Factor/Cluster; Comparisons: Continuous | Follow-Up Duration: 3.0 y; Results:; “Prudent” ♀, β: −0.03, SE: 0.06, p-trend=0.60; “Western” ♀, β: −0.08, SE: 0.06, p-trend=0.16; “Prudent” ♂, β: 0.04, SE: 0.07, p-trend=0.54; “Western” ♂, β: −0.08, SE: 0.07, p-trend=0.21; Summary: NS/Null: “Prudent” DP (♂, ♀) & CD; NS/Null: “Western” DP (♂, ♀) & CD | - Did not account for: SEP, Physical Activity, Smoking, Alcohol; - Diet assessment: FFQ once at baseline; - Outcome measurement: MMSE-modified at baseline & annually for 3 yrs; Funding: Canadian Institutes of Health Research
Daniel, 2021 ^19^; United States; Multi-Ethnic Study of Atherosclerosis (MESA); Analytic N=4169 (Exam 5); 2048 (change data); Participant characteristics:; - [underlined: Race and/or Ethnicity]:42% non-Hispanic White; - 11% Chinese; - 25% non-Hispanic Black; - 21% Hispanic; - [underlined: SEP]: Less than college degree, 59.6%; - Household income:; - <$20,000, 17.8%; - $20,000–34,999, 19.8%; - $35,000–50,000, 16.8%; - $50,000–99,999, 29.2%; - $100,000+, 16.5%; - [underlined: Selection:] Excluded those with extreme energy intake; those lost to f/u; those using Alzheimer’s medication | - DP Age(s): 45–84 y at baseline; mean age 60.4y; - DP(s) examined: DASH Score [Fung 2008]; - DP Components:; - DASH, Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy. Negative: Red and Processed Meat; Sweetened Beverages; Sodium; - DP Method(s): Index/Score; Comparisons: Categorical, DASH by quintiles (Q1, ref) | Follow-Up Duration: 10–17 y, ∼ total (diet assessed 2000–2002; outcome assessed 2010–2012 & 2016–2019); Results:; Global cognition (mean (SE) score); At exam 5; Q1, 84.13 (0.61); Q2, 83.66 (0.63); Q3, 83.59 (0.60); Q4, 83.93 (0.60); Q5, 84.07 (0.62); p-trend=0.41; At exam 6,; Q1, 82.15 (1.25); Q2, 82.37 (1.28); Q3, 82.08 (1.24); Q4, 82.35 (1.27); Q5, 82.74 (1.28); p-trend=0.73; Change; Q1, −0.24 (0.16); Q2, −0.21 (0.16); Q3, −0.25 (0.16); Q4, −0.29 (0.16); Q5, −0.16 (0.16); p-trend=0.37; Processing speed (mean (SE) score); At exam 5; Q1, 41.38 (1.31); Q2, 40.47 (1.36); Q3, 40.63 (1.29); Q4, 40.55 (1.30); Q5, 40.31 (1.35); p-trend=0.66; At exam 6; Q1, 38.54 (2.82); Q2, 38.51 (2.88); Q3, 39.24 (2.79); Q4, 37.91 (2.84); Q5, 37.02 (2.87); p-trend=0.35; Change; Q1, −0.30 (0.14); Q2, −0.33 (0.14); Q3, −0.30 (0.14); Q4, −0.36 (0.14); Q5, −0.34 (0.14); p-trend=0.75; Working memory (mean (SE) score); At exam 5; Q1, 14.83 (0.35); Q2, 14.56 (0.37); Q3, 14.55 (0.35); Q4, 14.80 (0.35); Q5, 14.71 (0.37); p-trend=0.52; At exam 6; Q1, 14.51 (0.73); Q2, 14.40 (0.74); Q3, 14.29 (0.72); Q4, 14.72 (0.74); Q5, 14.55 (0.74); p-trend=0.67; Change; Q1, −0.05 (0.14); Q2, −0.01 (0.14); Q3, −0.11 (0.14); Q4, −0.06 (0.14); Q5, −0.03 (0.14); p-trend=0.44; Summary: Null: DASH & global cognition, processing speed, working memory | - Did not account for: None (all); - Diet assessment: FFQ assessed once at baseline; - Outcome measurement: CASI (Cognitive Abilities Screening Instrument) for global cognition; DSC (Digit Symbol Coding) for processing speed; Digit Span test for working memory. Assessed twice-Exam 5 (2010–2012) and Exam 6 (2016–2019); Funding: NIH (NHLBI; NCATS)
de Crom, 2022 ^20^; Netherlands; Rotterdam Study (RS); Analytic N=8236; Participant characteristics:; - [underlined: Race and/or Ethnicity: NR]; - [underlined: SEP]: Education:; - Primary, 20.6% (baseline I), 6.8% (baseline II); - Lower, 42.6 % (baseline I), 43.3% (baseline II); - Intermediate, 28.1% (baseline I), 33.1 (baseline II); - Higher, 8.7% (baseline I), 16.7% (baseline II); - [underlined: Selection:] Excluded those without dietary data or with unreliable dietary data; those with dementia at baseline; no consent form; insufficient cognitive screening to assess dementia | - DP Age(s): 67.7–75.3 y at baseline; - DP(s) examined: Mediterranean-Dash Intervention for Neurodegenerative Delay diet (MIND) [Morris, 2015]; - Dutch Dietary Guidelines - 2015 [Voortman 2017]; - Mediterranean-based Diet Score (MedDietScore) [Panagiotakos 2007]; - DP Components:; - MIND: Positive: Green leafy vegetables; Vegetables; Beans; Berries; Nuts; Whole Grains; Seafood; Poultry; Olive oil; Wine. Negative: Red Meat; Cheese; Pastries and sweets; Butter and stick margarine; Fried/fast food; - Dutch-DG: Positive: Vegetables; Legumes; Fruit; Nuts; Whole Grains; Fish; Dairy Products; Unsaturated Fats and Oils; Tea. Negative: Replace Refined with Whole-Grain Products; Red Meat; Processed Meat; Alcohol; Sodium; - MedDietScore, Positive: Vegetables; Potatoes; Legumes; Fruit; Whole Grains; Fish; Olive Oil. Negative: Red and Processed Meat; Poultry; Full-Fat Dairy; Alcohol; - DP Method(s): Index/Score; Comparisons: Continuous, per SD | Follow-Up Duration: 15.6 y (mean; baseline I), 5.9 y (mean; baseline II); Results:; MIND; Baseline I, HR: 0.99, 95% CI: 0.94, 1.05; Baseline II, HR: 0.79, 95% CI: 0.70, 0.91; Dutch DG; Baseline I, HR: 1.01, 95% CI: 0.96, 1.07; Baseline II, HR: 0.89, 95% CI: 0.78, 1.02; MedDietScore; Baseline I, HR: 1.04, 95% CI: 0.97, 1.10; Baseline II, HR: 0.75, 95% CI: 0.66, 0.86; Summary: Inverse: MIND score (baseline II) & incident dementia (Null: baseline I); Inverse: MedDietScore (baseline II) & incident dementia (Null: baseline I); Null: Dutch DG (baseline 1 & II) & incident dementia | - Did not account for: SEP, Race and/or Ethnicity (Dutch); - n=1188 new Dx dementia; - Diet assessment: FFQ assessed once at baseline; - Outcome measurement: MMSE; Geriatric Mental Schedule (GMS) at baseline for exclusion and every 3–5 y during f/u; incident dementia also obtained through electronic health records from GPs & Regional Institute of Outpatients Mental Health Care; final Dx made by panel led by neurologist based on standard criteria for all-cause dementia (DSM-III-R), sub-Dx for Alzheimer’s Dz (NINCDS-ADRDA); Funding: Erasmus Medical Center and Erasmus University; Netherlands Organization for the Health Research and Development; the Research Institute for Diseases in the Elderly; the Ministry of Education, Culture and Science; the Ministry for Health, Welfare and Sports; the European Commission; and the Municipality of Rotterdam
de Crom, 2023 ^21^; The Netherlands; Rotterdam Study (RS); Analytic N=9543; Participant characteristics:; - [underlined: Race and/or Ethnicity: NR] (Dutch); - [underlined: SEP]: Education: 15% primary, 41% lower, 28% intermediate, 15% higher; - [underlined: Selection:] Excluded those with or who: missing/unreliable dietary data; Dem at baseline or not screened for Dem at baseline; undocumented reasons; or did not consent | - DP Age(s): 64y, mean; - DP(s) examined: adapted Plant-based diet index (aPDI; healthful/unhealthful, ahPDI/auPDI) [Satija, 2016, adapted by Chen, 2018]; - DP Components:; - aPDI: Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets; Negative: Animal fats; Low-fat milk; Low-fat yogurt; full-fat milk; full-fat yogurt; Cheese; Sugary-Dairy; Eggs, Fish/seafood; Red and Processed Meat; Unprocessed meat; Dessert and sugary dairy; - ahPDI: Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Negative: Sugar-sweetened beverages; Refined grains; Potatoes; Sweets; Animal fats; Low-fat milk; Low-fat yogurt; full-fat milk; full-fat yogurt; Cheese; Sugary-Dairy; Eggs, Fish/seafood; Red and Processed Meat; Unprocessed meat; Dessert and sugary dairy; - auPDI: Negative: Whole grains; Fruits; Vegetables; Nuts; Legumes; Tea/coffee; Animal fats; Low-fat milk; Low-fat yogurt; full-fat milk; full-fat yogurt; Cheese; Sugary-Dairy; Eggs, Fish/seafood; Red and Processed Meat; Unprocessed meat; Dessert and sugary dairy. Positive: Veg. Oils; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets; - DP Method(s): Index/Score; Comparisons: Continuous per-10pt increase and categorical by quintiles (QF, HR: 1 REF) for aPDI, ahPDI, auPDI | Follow-Up Duration: 14.5y, mean; Results:; aPDI & Dem; per-10-pt, 0.99 (0.91, 1.08); Q2, HR: 1.01 (0.85, 1.19); Q3, HR: 1.09 (0.92, 1.30); Q4, HR: 1.01 (0.85, 1.20); Q5, HR: 1.04 (0.87, 1.24); ahPDI & Dem; per-10-pt, 0.93 (0.75, 1.01); Q2, HR: 0.94 (0.80, 1.12); Q3, HR: 0.84 (0.71, 1.00); Q4, HR: 0.77 (0.65, 0.92); Q5, HR: 0.89 (0.74, 1.06); auPDI & Dem; per-10-pt, 1.02 (0.94, 1.10); Q2, HR: 1.15 (0.96, 1.37); Q3, HR: 1.13 (0.95, 1.34); Q4, HR: 1.25 (1.05, 1.50); Q5, HR: 1.05 (0.87, 1.26); Summary: NS/Null: aPDI & risk of Dem; NS/Inverse: ahPDI & risk of Dem; NS/Positive: auPDI & risk of Dem | - Did not account for: SEP, Race and/or Ethnicity (Dutch); - Results were similar after multiple analyses (i.e., by Alz, excluding first 5y f/U; sex, age, apoE status); - Diet assessment: FFQ once at baseline, different for RS-I and II vs. III; - Outcome measurement: Dem (or Alz) based on MMDS <26 or GMS >0 further screened with Cambridge exam, monitoring with medical records database and final consensus with neurological expert panel using DSM-III-R; cases n=1472; Funding: Erasmus Medical Centre and Erasmus University, Rotterdam, Netherlands Organization for the Health Research and Development (ZonMw); the Research Institute for Diseases in the Elderly (RIDE); the Ministry of Education, Culture and Science; the Ministry for Health, Welfare and Sports; the European Commission (DG XII); and the Municipality of Rotterdam
Dhana, 2021 ^22^; United States; Rush Memory and Aging Project (MAP); Analytic N=569; Participant characteristics:; - [underlined: Race and/or Ethnicity: NR] (“mostly white”); - [underlined: SEP]: Education, ∼15 y (mean); - [underlined: Selection:] Excluded those without valid dietary data, cognitive testing; those with mild cognitive impairment at baseline in sensitivity analyses | - DP Age(s): ≥65 y at baseline;; - DP(s) examined: Mediterranean-Dash Intervention for Neurodegenerative Delay diet (MIND) [Morris, 2015]; - DP Components:; - Positive: Green leafy vegetables; Vegetables; Beans; Berries; Nuts; Whole Grains; Seafood; Poultry; Olive oil; Wine. Negative: Red Meat; Cheese; Pastries and sweets; Butter and stick margarine; Fried/fast food; - DP Method(s): Index/Score; Comparisons: Continuous, per SD | Follow-Up Duration: NR; Results:; Global cognition (proximate to death) β: 0.119, SE: 0.040, p-trend=0.003; Results unchanged when including AD pathology in model; MIND & AD pathology (post-mortem), β: −0.013, SE: 0.024, p=0.578; Summary: Positive: MIND score & (better) global cognition | - Did not account for: SEP, Race and/or Ethnicity, Physical activity, Anthropometry, Smoking; - ∼70% women; results similar when Alzheimer’s Dz pathology included in model; - Diet assessment: Mean ∼3.5 dietary assessments; - Outcome measurement: 19 cognitive tests, composite score for global cognition: including 7 episodic memory tests (immediate and delayed recall of the East Boston Story and Story A from Logical Memory, Word List Memory, Word List Recall, Word List Recognition); 3 semantic memory tests (15-item Boston Naming Test, Verbal Fluency, 15-item word reading test); 3 working memory tests (Digit Span Forward, Digit Span Backward, Digit Ordering).; Funding: NIA/NIH
Flores, 2023 ^23^; United States; Geisinger Rural Aging Study (GRAS); Analytic N=2232; Participant characteristics:; - [underlined: Race and/or Ethnicity]: Non-Hispanic White, ∼99%; Other, 0.1–0.3%; Unknown or missing, 0.4–1.0%; - [underlined: SEP]: Education level:; - Below college degree, 71–86%; - College degree, 8–18%; - Graduate degree, 2–6%; - Unknown, 4–7%; - [underlined: Selection:] Excluded those with missing dietary data; those with missing f/u data; those enrolled after study baseline (2009) or disenrolled before study baseline; those with prevalent dementia at baseline | - DP Age(s): 84 y, mean (≥80 y); - DP(s) examined: Dietary Screening Tool (DST) based on HEI-2005 (McCullough 2000) [Bailey 2007]; - DP Components:; - DST, Positive: Vegetables; Whole Fruit and Juice; Total and Whole Grains; Lean Proteins (chicken or turkey; fish or seafood not fried); Dietary Supplement Use. Negative: Added fats, sugars, and sweets (including alcoholic beverages); Processed Meats (cold cuts, hot dogs, lunch/deli meats; bacon or sausage. Neutral: Dairy (milk, cheese, yogurt); - DP Method(s): Index/Score; Comparisons: Categorical, tertiles | Follow-Up Duration: 6.9 y (mean); 11.7 y maximum f/u; Results:; DST & Dem (all-cause); T1, HR: 1, ref; T2, HR: 1.05, 95% CI: 0.82, 1.34; T3, HR: 1.01, 95% CI: 0.79, 1.29; p-trend=0.95; DST & Dem (other incl. vascular); T1 vs. T3, HR: 1.00, 95% CI: 0.74, 1.32, p-trend=0.99; DST & Alz; T1 vs. T3, HR: 1.04, 95% CI: 0.68, 1.60, p-trend = 0.86; Summary: NS/Null: DST & all-cause Dem, other Dem, Alz | - Did not account for: None (all); - Study enrollment began in 1994, baseline for the analyses were in 2009 when DST survey sent; - Diet assessment: DST survey questionnaire (25 items) assessed once at baseline; - Outcome measurement: Incident dementia collected from EHRs; Funding: USDA, Agricultural Research Service
Galbete, 2015 ^24^; Spain; SUN (Seguimiento Universidad de Navarra) Study subcohort; Analytic N=823; Participant characteristics:; - [underlined: Race and/or Ethnicity: NR] (100% recruited from Spanish universities); - [underlined: SEP]: Education, University: 5.4 y (mean); - [underlined: Selection:] Spanish university graduates; Excluded those with incorrect genotype for APOE; extreme energy intake; missing covariate data | - DP Age(s): 61.9 y (mean), 55+ at baseline; - DP(s) examined: Mediterranean Diet Score (MDS) [Trichopolou 2003]; - DP Components:; - MDS, Positive: Vegetables; Legumes; Fruit, Nuts; Cereals; Fish; MUFA/SFA. Negative: Red and Processed Meat; Dairy Products. Neutral: Alcohol; - DP Method(s): Index/Score; Comparisons: Categorical, low (0–3 pts), moderate (4–6 pts), high (7–9 pts) | Follow-Up Duration: 2 y; Results:; TICS-m (range 0–54 pts); Low, mean: 34.39 pts, 95% CI: 34.13, 34.64; Moderate, mean: 34.19, 95% CI: 33.99, 34.39; High, mean: 34.81.95% CI: 34.41, 35.21; Δ CD (ΔTICS-m); Low, adjusted difference: −0.43, 95% CI: −0.92, 0.05, p-trend=0.080; Moderate, adjusted difference: −0.62, 95% CI: −1.07, −0.18, p-trend=0.006; High, adjusted difference: 0, ref; Low + Moderate (vs. high), adjusted difference: −0.56, 95% CI: −0.99, −0.13, p-trend=0.011; Summary: Positive: MDS & TICS-m at 2y f/u; Inverse: MDS & CD (moderate vs. high; low+moderate vs. high) at 2y f/u; NS/Null: MDS & CD (low vs. high) at 2y f/u | - Did not account for: SEP, Race and/or Ethnicity; - 71% male. Mean difference in TICS-m score at 2 y f/u across MDS adherence <1 pt (i.e., statistically significant but may be less clinically significant); - Diet assessment: FFQ once at baseline; - Outcome measurement: CD and CFx based on TICS-m (Telephone Interview of Cognitive Status-modified), includes five domains: immediate memory, delayed recall, orientation, attention/calculation, language; Funding: Spanish government; Navarra Regional Government; University of Navarra
Gelber, 2012 ^25^; United States; Honolulu-Asia Aging Study (HAAS); Analytic N=3468; Participant characteristics:; - [underlined: Race and/or Ethnicity]:100% Japanese ancestry; - [underlined: SEP]: NR; - [underlined: Selection:] Excluded females; those with missing baseline data (diet, physical acivity, alcohol, BMI); those with cognitive impairment at baseline (CASI score <74); | - DP Age(s): 52y, mean; - DP(s) examined: Diet score [Gelber, 2012]; - DP Components:; - Diet score: Highest in (top 60% in Q5 intakes of) fruit, vegetables (not salted Japanese types), fish, cereals (whole and refined), MUFA/SFA; Lowest in meat, dairy; and mild-moderate alcohol [excluded legume due to high Na+ content]; - DP Method(s): Index/Score; Comparisons: Categorical: “Low-risk” vs. High diet score (top 60% scores, OR: 1 REF) | Follow-Up Duration: 25y, total; Results:; Low vs. High & Dem, OR: 1.20, 95% CI: 0.88, 1.63; Low vs. High & Vascular Dem, OR: 1.00, 95% CI: 0.62, 1.62; Low vs. High & Alz, OR: 1.36, 95% CI: 0.89, 2.08; Summary: NS/Inverse: Diet score & Dem; Alz [Null: Vascular Dem] | - Did not account for: Co-exposures: Physical Activity, Smoking; - Diet assessment: 24h-recall once at baseline, validated against dietary record in subset; - Outcome measurement: Alz & Dem based on scores < 74 of 100 on the Cognitive Abilities Screening Instrument (CASI), a composite of the MMSE, mMMSE, and Hasegawa Dementia Screener. DMS-III criteria applied for Dx; Funding: NIA; NHLBI; VA
Glans, 2023^26^ Sweden; Malmo Diet and Cancer study (MDCS); Analytic N=28025; Participant characteristics:; - [underlined: Race and/or Ethnicity: NR]; - [underlined: SEP]: Education level:; - Elementary school (<8 yrs), 42.0%; 9–12 yrs, 35.1%; >/=13 yrs, 22.9%; - [underlined: Selection:] Excluded those with ‘language problems and mental incapacity’; with incomplete dietary data; incomplete data on education or time to Dx | - DP Age(s): 58.1 y (mean); - DP(s) examined: Swedish Dietary Guidelines Score (SDGS); - modified Mediterranean Diet Score (mMDS) [Panagiotakos, 2007 modified by Martinez-Gonzalez, 2012]; - DP Components:; - SDGS: Positive: dietary fiber (from non-alcohol energy); fish and shellfish; fruit and vegetables. Negative: added sugar (from non-alcohol energy); red and processed meat; - mMDS: Positive: vegetable oils; vegetables (including legumes); fruits; wine; fish; seafood; nuts and seeds. Negative: red and processed meat; butter, margarine, and cream; soda; pastries; candy.; - DP Method(s): Index/Score; - Comparisons: Categorical, tertiles; Continuous, per 1-pt | Follow-Up Duration: 15.5 y; Results:; All-cause dementia; SDGS; T1, HR: 1, ref; T2, HR: 1.02, 95% CI: 0.92, 1.12; T3, HR: 0.95, 95% CI: 0.82, 1.10; Per 1-pt, HR: 0.99, 95% CI: 0.95, 1.03; mMDS; T1, HR: 1, ref; T2, HR: 0.94, 95% CI: 0.83, 1.06; T3, HR: 0.95, 95% CI: 0.76, 1.18; Per 1-pt, HR: 1.00, 95% CI: 0.96, 1.04; Vascular dementia; SDGS; T1, HR: 1, ref; T2, HR: 0.97, 95% CI: 0.79, 1.18; T3, HR: 1.00, 95% CI: 0.73, 1.35; Per 1-pt, HR: 1.00, 95% CI: 0.93, 1.08; mMDS; T1, HR: 1, ref; T2, HR: 0.95, 95% CI: 0.74, 1.22; T3, HR: 1.09, 95% CI: 0.70, 1.70; Per 1-pt, HR: 1.06, 95% CI: 0.98, 1.15; Abnormal CSF Aβ42 (n=777); SDGS; T1, OR: 1, ref; T2, OR: 1.37, 95% CI: 0.94, 2.01; T3, OR: 1.34, 95% CI: 0.76, 2.36; Per 1-pt, OR: 1.15, 95% CI: 0.99, 1.33; mMDS; T1, OR: 1, ref; T2, OR: 1.01, 95% CI: 0.37, 1.79; T3, OR: 0.82, 95% CI: 0.37, 1.79; Per 1-pt, OR: 0.99, 95% CI: 0.85, 1.15; Alzheimer’s Disease; SDGS; T1, HR: 1, ref; T2, HR: 1.06, 95% CI: 0.94, 1.21; T3, HR: 1.01, 95% CI: 0.84, 1.22; Per 1-pt, HR: 0.99, 95% CI: 0.95, 1.04; mMDS; T1, HR: 1, ref; T2, HR: 0.91, 95% CI: 0.77, 1.07; T3, HR: 0.87, 95% CI: 0.66, 1.16; Per 1-pt, HR: 0.99, 95% CI: 0.94, 1.04; Summary: Null: SDGS & Dem (all-cause, vascular), Alzheimer’s Dz, abnormal CSF Aβ42; Null: mMDS & Dem (all-cause, vascular), Alzheimer’s Dz, abnormal CSF Aβ42 | - Did not account for: SEP, Race and/or Ethnicity; - CSF Aβ42 presented as exploratory outcome, obtained only from subsample; sensitivty analyses excluding those Dx with dementia <5 yrs from diet assessment (to reduce possible bias of cognitive impairment affecting dietary intake) found similar results to m; - Diet assessment: Combination of 7-d diary, FFQ, and interview (w/trained staff) assessed once at baseline; - Outcome measurement: All-cause dementia, Alzheimer’s Dz and vascular dementia diagnosed based on registered Dx from Swedish National Patient Register (covers both inpatient and outpatient). CSF Aβ42 obtained from subsample referred to Memory Clinic at Skane University Hospital, udnerwent lumbar puncture; Funding: Swedish Research Council, Knut and Alice Wallenberg foundation, Marianne and Marcus Wallenberg foundation, Strategic Research Area MultiPark, Swedish Alzheimer Foundation, Swedish Brain Foundation, Parkinson foundation of Sweden, Konung Gustaf V:s och Drottning Victorias Frimurarestiftelse, the Skåne University Hospital Foundation, Regionalt Forskningsstod, Swedish federal government
Granic, 2016 ^27^; United Kingdom; Newcastle 85+ Study; Analytic N=791; Participant characteristics:; - [underlined: Race and/or Ethnicity: NR] (“white population of North European descent”); - [underlined: SEP]: Education:; - 0–9 years, 64.1%; - 10–11 years, 23.4%; - 12+ years, 12.4%; - Marital status:; - 69.4% not married; - Social class:; - Routine/manual professions, 51.1%; - Intermediate professions, 14.5%; - Higher managerial/administrative, 34.4%; - [underlined: Selection:] Included those born in 1921; excluded those with incomplete diet, health assessment, and GP record data | - DP Age(s): 85+ y at baseline; - DP(s) examined: n/a; - DP Components:; - DP1 (High Red Meat): Positive: red meats/meat dishes; potatoes/potato dishes; gravy; legumes (including baked beans); unsaturated fats spreads; % energy from protein and starch. Negative: butter; - DP2 (Low Meat): Positive: fruits; nuts; whole grains and cereal products; fish and seafood; eggs; soups; low and high fat dairy; coffee and alcohol. Negative: meats/meat dishes(red and processed meats; bacon and ham; poultry); gravy; potatoes/potato dishes; protein. Moderate: butter; - DP3 (High Butter): Positive: butter. Negative: unsaturated and saturated fat spreads and oils (margarine, vegetable oils fat spreads and lard); MUFA, SFA, total fat. Negative: PUFA and MUFA/SFA ratio. Moderate: red meats/meat dishes.; - DP Method(s): Factor/Cluster; Comparisons: Continuous (DP 1 or DP 3 vs. DP 2, ref) | Follow-Up Duration: 3y, 5y; Results:; Global cognition (MMSE), 5y; DP1, β: −0.02, SE: 0.04, p-trend=0.55; DP3, β: 0.01, SE: 0.04, p-trend=0.90; Attention-specific tasks, 3y; SRT; DP1, β: 0.003, SE: 0.01, p-trend=0.73; DP3, β: 0.004, SE: 0.01, p-trend=0.52; CRT; DP1, β: 0.0002, SE: 0.01, p-trend=0.99; DP3, β: 0.01, SE: 0.01, p-trend=0.96; DV1; DPI, β: −0.002, SE: 0.01, p-trend=0.61; DP3, β: 0.003, SE: 0.01, p-trend=0.48; PoA; DPI, β: 0.004, SE: 0.01, p-trend=0.59; DP3, β: 0.004, SE: 0.01, p-trend=0.60; RTV; DPI, β: −0.01, SE: 0.01, p-trend=0.29; DP3, β: −0.01, SE: 0.01, p-trend=0.25; CoA; DP1, β: −0.06, SE: 0.10, p-trend=0.54; DP3, β: −0.01, SE: 0.10, p-trend=0.89; Cognitive Impairment; DP1, OR: 1.91, 95% CI: 1.22, 3.01, p-trend=0.005; DP3, OR: 1.42, 95% CI: 0.90, 2.26, p-trend=0.13; Summary: NS/Null: DP1 or DP3 vs. DP2 & Global cognition, Attention (all measures); Positive: DP1 vs DP2 & CD; NS/Null: DP3 vs DP2 & CD | - Did not account for: Race and/or Ethnicity (likely White, European-descent); - Results for global cognition did not differ when men & women analyzed separately; cognitive impairment results did not differ when excluding those with dementia/Alzheimer’s disease Dx; - Diet assessment: 24-h recall assessed once at baseline (2 different days); - Outcome measurement: CD defined as MMSE score ≤25; Assessments for global cognition were MMSE; attention tasks were CoA (continuity of attention), CRT (choice reaction time), DVT (digit vigilance reaction time), PoA (power of attention), RTV (reaction time variability), SRT (simple reaction time); Funding: NR
Gregory, 2022 ^28^; Multiple EU countries (Greece, Spain, Italy, UK, Belgium, UK, France, Sweden, Switzerland, Netherlands); European Prevention of Alzheimer’s Dementia Longitudinal Cohort Study (EPAD LCS); Analytic N=1826; Participant characteristics:; - [underlined: Race and/or Ethnicity: NR]; - [underlined: SEP]: Education, ∼14.4–14.6y mean; - [underlined: Selection:] Excluded those with or who had missing dietary, cognitive, or covariate data, < 50 y at baseline; Those included were more likely to be ApoEe4 carriers, younger, live in Mediterranean region | - DP Age(s): 65.7, mean; - DP(s) examined: Mediterranean Diet Adherence Screener (MEDAS) [Schroder 2011; modifications Shannon, 2019 (Dairy included)]; - DP Components:; - mMEDAS, Positive: Vegetables; Pulses; Fruit; Nuts; Fish/Seafood; White Meat Over Red Meat; Olive Oil; Olive Oil as Principal Cooking Fat; Red Wine; Sofritas (dishes with tomato, garlic, onion, leek, olive oil). Negative: Commercial Pastries; Red Meat; Dairy; Animal fat; Sugar-Sweetened Beverages (carbonated);; - DP Method(s): Index/Score; Comparisons: Continuous, MEDAS | Follow-Up Duration: up to 3y (varied from 1 up to 6 visits); Results:; MEDAS & FMT, slope: 0.10, SE: 0.03, t:3.13, 95% CI: 0.04, 0.17, p=0.002; MEDAS & RBANS, slope: −0.03, SE: 0.11, t: −0.30, 95% CI: −0.26, 0.19, p=0.76; longitudinal data between MEDAS & individual domains NR; Summary: Inverse: MEDAS & FMT; NS/Null: MEDAS & RBANS | - Did not account for: SEP, Race and/or Ethnicity; - Diet assessment: Questionnaire at baseline used (also collected at F/U); - Outcome measurement: CD based on cognitive battery of tests [Four Montain Test (FMT); MCI/Alz: Repeatable Battery for the Assessment of Neuropsychological Status(RBANS)]; Funding: EU/EFPIA Innovative Medicines Initiative Joint Undertaking EPAD; Alzheimer’s Association Grant; MRC
Guo, 2021 ^29^; United States; Washington Heights-Inwood Columbia Aging Project (WHICAP); Analytic N=1987; Participant characteristics:; - [underlined: Race and/or Ethnicity]: White, 28.23%; Black, 29.44%; Hispanic, 40.36%; Other, 1.96%; - [underlined: SEP]: Mean years of education, 10.94; - [underlined: Selection:] Excluded those with dementia at baseline; those with no f/u data; missing data on variables of interest | - DP Age(s): ≥65 y; ∼75 y (mean); - DP(s) examined: American Heart Association (AHA) Life’s Simple 7 (LS7) - dietary component; - DP Components:; - LS7, Positive: Fruits and Vegetables (≥4.5 serv./d); Fish (≥two, 3.5 oz/wk). Negative: Sodium (<1500 mg/d); Sugar-sweetened beverages (<36 oz/wk); - DP Method(s): Index/Score; - Comparisons: Categorical, poor (0–1 dietary components), intermediate (2–3 components), or optimal (4 components); Continuous, per 1-pt | Follow-Up Duration: 5.84 y (median); range 0.94 – 17.68 y; Results:; Poor, HR: 1, ref; Intermediate, HR: 0.89, 95% CI: 0.69, 1.14; Optimal, HR: 0.69, 95% CI: 0.33, 1.44; Per 1 pt, 0.87, 95% CI: 0.7, 1.09 p-trend=0.865; Summary: Null: LS7 diet & incident dementia | - Did not account for: SEP, Physical Activity, Anthropometry, Smoking, Alcohol; - Results remained NS when stratified by APOE-e4 carriers vs. non-carriers; Effects of physical activity, smoking, and BMI on incident dementia examined separately but not included as covariates in diet analyses, physical activity significnatly inversely as; - Diet assessment: FFQ assessed once at baseline; diet was one component of 7-item overall lifestyle score; Whole grains excluded from construction of DP metric due to incomplete data on intake by FFQ; - Outcome measurement: DSM-IV Dx - consensus of panel of neuologists, psychiatrists, and neuropsychologists based on battery of memory, language, orientation, abstract reasoning, visuospatial ability; Funding: NIH
Hsiao, 2022 ^30^; Taiwan; Taiwan Longitudinal Study on Aging (TLSA); Analytic N=3213; Participant characteristics:; - [underlined: Race and/or Ethnicity: NR] (Taiwanese); - [underlined: SEP]: Education: 30% none, 47% primary; 24% junior/senior high/college; - Married 73%, Widowed 23%; - [underlined: Selection:] Excluded those with or who had missing 4y F/U data, emigrated, resided in nursing home, proxy responders, unknown demographic/dietary/outcome data | - DP Age(s): 50 to 64y, 40%; 65 to 74y, 38%, 75+, 22%; - DP(s) examined: modified dietary variety score (DVS) [Kumagai, 2003]; - DP Components:; - DVS Q5 vs. Q1 reflects higher intakes of: Vegetables (dark colored); Fruit; Legumes; Dairy; Meat; Poultry; Fish; Seafood; Tea; - DP Method(s): Index/Score; Comparisons: Categorical, DVS quintiles (Q1, aOR: 1 REF) | Follow-Up Duration: ∼4y; Results:; DVS & CD; Q2, OR: 0.99, 95% CI: 0.73, 1.35; Q3, OR: 0.96, 95% CI: 0.72, 1.29; Q4, OR: 0.92, 95% CI: 0.70, 1.20; Q5, OR: 0.76, 95% CI: 0.57, 1.03; Summary: Null: DVS & cognitive decline | - Did not account for: Race and/or Ethnicity (all Taiwanese), SEP (marital status), Smoking; - Indirect exposure with unclear classification; - Diet assessment: FFQ assessed once at baseline; - Outcome measurement: CD derived from Short Portable Mental Status Questionnaire, the Rey Auditory Verbal Learning Test, and the Wechsler Adult Intelligence Scale; Funding: Ministry of Science and Technology, Taiwan; National Health Research Institutes, Taiwan
Hu, 2020 ^31^; United States; Atherosclerosis Risk in Communities (ARIC) study; Analytic N=13630; Participant characteristics:; - [underlined: Race and/or Ethnicity]:23–28% Black; - [underlined: SEP]: 25–46% with college education (higher in higher HEI-2015 adherence); - [underlined: Selection:] Excluded those who were not Black or white; those who were Black from Minneapolis, Minnesota or Washington County (Maryland); those who did not fill out more than 15 FFQ responses; with extreme energy intakes; Hx stroke at baseline; missing data on covariates; with insufficient data to calculate 4 dietary scores | - DP Age(s): 54 y(mean), 45–64 y at baseline; - DP(s) examined: Healthy Eating Index (HEI-2015) [Krebs-Smith 2018]; - Alternative HEI (AHEI)-2010 [Chiuve 2012]; - Alternate Med Diet Score (aMED) [Fung 2005]; - DASH Score [Fung 2008]; - DP Components:; - HEI-2015: Positive: Total Vegetables; Greens and Beans; Total Fruit; Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; PUFA+MUFA/SFA. Negative: Refined Grains; Added Sugars; SFA; Sodium; - AHEI-2010: Positive: Vegetables (not potatoes, French fries); Fruit; Legumes and Nuts; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA. Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Trans FA; Sodium. Neutral: Alcohol; - aMED: Positive: Vegetables (not potatoes); Legumes; Fruit; Nuts; Whole Grains; Fish; MUFA/SFA. Negative: Red and Processed Meat. Neutral: Alcohol; - DASH: Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy. Negative: Red and Processed Meat; Sweetened Beverages; Sodium; - DP Method(s): Index/Score; Comparisons: Categorical, quintiles | Follow-Up Duration: 27 y (median); Results:; HEI-2015 & Dem; Q1, HR: 1, ref; Q2, HR: 0.86, 95% CI: 0.75, 1.00; Q3, HR: 0.89, 95% CI: 0.77, 1.02; Q4, HR: 0.90, 95% CI: 0.78, 1.04; Q5, HR: 0.86, 95% CI: 0.74, 0.99; p-trend=0.1; AHEI-2010 & Dem; Q1, HR: 1, ref; Q2, HR: 1.06, 95% CI: 0.93, 1.22; Q3, HR: 0.99, 95% CI: 0.86, 1.13; Q4, HR: 0.92, 95% CI: 0.80, 1.06; Q5, HR: 1.04, 95% CI: 0.91, 1.20; p-trend=0.9; aMED & Dem; Q1, HR: 1, ref; Q2, HR: 1.04, 95% CI: 0.90, 1.20; Q3, HR: 1.02, 95% CI: 0.88, 1.17; Q4, HR: 0.99, 95% CI: 0.86, 1.15; Q5, HR: 1.01, 95% CI: 0.88, 1.16; p-trend=0.9; DASH & Dem; Q1, HR: 1, ref; Q2, HR: 1.06, 95% CI: 0.93, 1.21; Q3, HR: 1.03, 95% CI: 0.89, 1.20; Q4, HR: 0.97, 95% CI: 0.85, 1.11; Q5, HR: 1.10, 95% CI: 0.96, 1.26; p-trend=0.5; Summary: Inverse/NS: HEI-2015 & incident Dementia; Null: AHEI-2010, aMED, DASH & incident Dementia | - Did not account for: SEP; - Diet assessment: FFQ at visit 1 (1987–1989) and visit 3 (1993–1995). Only visit 1 data used if participants developed dementia between visit 1 and 3; - Outcome measurement: Demntia defined/obtained by: 1) adjudicated dementia based on a complete neuropsychological battery, informant interviews and expert review at ARIC Neurocognitive Study visits (visits 5 and 6); 2) dementia determined from telephone interviews with participant or informant; or 3) dementia based on a prior hospitalization or death code for dementia.; Funding: NIH
Jia, 2023 ^32^; China; China Health and Nutrition Survey (CHNS); Analytic N=4173; Participant characteristics:; - [underlined: Race and/or Ethnicity: NR] (Chinese); - [underlined: SEP]: Education:; - Primary school, 54.9%; - Middle school, 22.4%; - high school, 22.8%; - Household income level:; - Low, 30.9%; - Medium, 33.1%; - High, 36.0%; - [underlined: Selection:] Excluded those age 55–59 y AND with moderate/vigorous physical activity; with extreme energy intake; outliersin annual change BMI; those missing covariate data | - DP Age(s): 63.7 y (mean); 55+ y at baseline; - DP(s) examined: China Elderly Dietary Guidelines Index 2022 (CDGI 2022-E); - DP Components:; - Positive: whole grains and mixed beans (≥100 g/day); vegetables (≥450g/ day for males; ≥350g/day for females); fruits (≥300g/ day for males; ≥200g/day); dairy (≥300g/day); soybeans and nuts (≥30g/day for males; ≥25g/day for females). Negative: cooking oil (<27.5 g/day for males, <25 g/day for females); salt (<5 g/day); alcohol (<15 g/day). Moderate: grains, beans, and tubers (200–300g/day; 50–65% of energy); fish/seafood (50–75g/day for males, 40–50g/day); meat and poultry (50–75g/day for males, 40–50g/day for females); eggs (50g/day for males, 40g/day for females); - DP Method(s): Index/score; Comparisons: Categorical, tertiles | Follow-Up Duration: NR; Results:; Global cognitive score (All participants); T1, 0, ref; T2, β: 0.057, 95% CI: −0.229, 0.344; T3, β: 0.704, 95% CI: 0.394, 1.015; p-trend<0.001; Global cognitive score (<65 y at baseline); T1, 0, ref; T2, β: 0.098, 95% CI: −0.265, 0.461; T3, β: 0.969, 95% CI: 0.567, 1.370; p-trend<0.001; Global cognitive score (≥65 y at baseline); T1, 0, ref; T2, β: 0.013, 95% CI: −0.453, 0.480; T3, β: 0.402, 95% CI: −0.089, 0.892; p-trend=0.099; Poor cognition (all participants); T1, OR: ref; T2, OR: 1.017, 95% CI: 0.884, 1.171; T3, OR: 0.820, 95% CI: 0.698, 0.965; p-trend=0.022; Poor cognition (<65 y at baseline); T1, OR: 1, ref; T2, OR: 0.992, 95% CI: 0.823, 1.195; T3, OR: 0.802, 95% CI: 0.641, 1.0; Summary: Positive: CDGI 2022-E & Global cognition (all participants; participants <65 y at baseline); Inverse: CDGI 2022-E & poor cognition (all participants); Null: CDGI 2022-E & Global cognition (participants ≥ 65 y at baseline); Null: CDGI 2022-E & poor cognition (participants <65 y at baseline; participants ≥ 65 y at baseline) | - Did not account for: Race and/or Ethnicity; - “CDGI 2018-E is suitable for old population in years of 60 and above, as well as adults aged more than 18 years with light physical activity”-this seems to be the reason for excluding those ages 55–59 with moderate/vigorous PA; - Diet assessment: Three consecutive 24-hr recalls (once at baseline?); - Outcome measurement: TICS-m; poor cognition defined as first (lowest) quartile of score which corresponds to <9 points; Funding: Chinese Institute of Food Science and Technology; NIH; Eunice Kennedy Shriver National Institute of Child Health and Human Development
Keenan, 2020 ^33^; United States; Age-Related Eye Disease Studies 2; Analytic N=4757; Participant characteristics:; - [underlined: Race and/or Ethnicity]:97% White; 3% Non-White; - [underlined: SEP]: Education: 48% at least some college; 30% high-school or less; - [underlined: Selection:] Excluded those with age-related macular degeneration at baseline; with conditions that would make follow-up or medication compliance difficult (including dementia) | - DP Age(s): ∼73y; 55–80 y at baseline; - DP(s) examined: Alternate Med Diet Score (aMED) [Fung 2005], only RM not R&PM; - DP Components:; - aMED, Positive: Vegetables (not potatoes); Legumes; Fruit; Nuts; Whole Grains; Fish; MUFA/SFA. Negative: Red Meat. Neutral: Alcohol; - DP Method(s): Index/Score; Factor/Cluster; Comparisons: Categorical, aMED tertiles (T1, OR: 1 ref) and linear trend | Follow-Up Duration: 9y, mean (∼6.5y to last cognitive test); Results:; aMED tertiles & CD (TICS-m); T2, OR: 0.83, 95% CI: 0.69, 1.00; p=0.047; T3, OR: 0.67, 95% CI: 0.56, 0.81; p<0.001; p-trend<0.001; aMED tertiles & CD (rate of change in TICS-m score), 0.22; aMED T1 vs. T3 & mean rate of change in CD at 2y: 1; at 4y: 0.9; at 10y: 1; p=0.; aMED tertiles & MCI (TICS-m); T2, OR: 0.76, 95% CI: 0.63, 0.91; p=0.003; T3, OR: 0.56, 95% CI: 0.47, 0.67; p<0.001; p-trend<0.001; aMED tertiles & MCI (composite); T2, OR: 0.68, 95% CI: 0.53, 0.87; p=0.003; T3, OR: 0.48, 95% CI: 0.37, 0.63; p<0.001; p-trend<0.; Summary: Inverse: aMED & CD or TICS-m after 2y, 4y, or 10y | - Did not account for: Education (MCI); SEP; Anthropometry; Physical activity; - Diet assessment: FFQ assessed once at randomization (baseline of RCT); - Outcome measurement: CD at 2y, 4y, 10y defined as rate of change in CFx scores based on TICS-M <30 and composite score in lowest decile; CD based on sum of z-scores from TICS-M (AREDS 2 only) with battery of tests (Buschke recall and word; Logical memory I and II; Animal; Letter fluency); Absolute TICS-M and composite scores also reported; Funding: NEI; NIH, HHS
Kjeldsen, 2022 ^34^; Denmark; Copenhagen General Population Study; Analytic N=94184; Participant characteristics:; - [underlined: Race and/or Ethnicity]:100% White; - [underlined: SEP]: HH Income “Low”: ∼31–52% (defined as <57,520 USD); - Education, 7–18% less than 8y; - [underlined: Selection:] Excluded those with or who had: Dem at baseline; incomplete/outlier dietary data; missing all data or date of birth/death, no consent, ethnicity other than Danish, or emigrated; Participants who were excluded were more likely, be women, have low HH income; <8y education, higher BMI, inactive, more tobacco. | - DP Age(s): 58y, mean; - DP(s) examined: Danish DG [Ewers, 2021]; - DP Components:; - Danish DG: Positive: Vegetables; Fruit; Fish; Unsaturated fat Negative: Cold meat (luncheon); Saturated fat; Sugar-sweetened beverages; Fast food; [did not include lean meat, dairy, whole grain, or water]; - DP Method(s): Index/Score; Comparisons: Categorical, Low or Intermediate vs. High (Ref) Danish DG score | Follow-Up Duration: 9y, median; Results:; non-Alz Dem,; Intermediate, HR: 1.14, 95% CI: 0.92, 1.40; Low, HR: 1.35, 95% CI: 1.03, 1.79; p-trend=0.04; Alz,; Intermediate, HR: 1.11, 95% CI: 0.96, 1.27; Low, HR: 1.01, 95% CI: 0.82, 1.25; p-trend=0.63; Summary: Inverse: Low Danish DG alignment (vs. High) & Higher risk of Dem (non-Alz);; NS/Inverse: Low Danish DG alignment (vs. High) & Higher risk of Alz | - Did not account for: None (all); - Results similar in analyses excluding those with less than 2 yrs follow-up; - Diet assessment: FFQ assessed diet twice; Change in DP assessed in a sub-set (∼34%); - Outcome measurement: Alz & Dem (all-cause) based on Danish Registries for patients/death; n=2086 cases (Dem, 701; Alz 1385); Funding: Lundbeck Foundation; Danish Heart Foundation
Lai, 2023 ^35^; Singapore; Singapore Chinese Health Study; Analytic N=861; Participant characteristics:; - [underlined: Race and/or Ethnicity]:100% Chinese; - [underlined: SEP]: Education: 36–46% none, 43–47% primary; 11–17% secondary+; - Married 77%; - [underlined: Selection:] Excluded those with or who: were blind, deaf or unable to complete cognitive test; incomplete dietary data at SG90 F/U | - DP Age(s): 65y, mean (60 to 74y at baseline); - DP(s) examined: modified DASH Score [Fung 2008]]; - DP Components:; - mDASH, Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Total (not just LF) Dairy. Negative: Red and Processed Meat; Sweetened Beverages. [excluded sodium]; - DP Method(s): Index/Score; Comparisons: Continuous, “Consistently high” DASH scores at baseline and over time vs. “Consistently low” with modest decline in DASH over time as REF | Follow-Up Duration: ∼20y and 23y total (F/U 3 and 4); Results:; Consistently high vs. low DASH & CD, OR: 0.71, 95%CI: 0.51, 0.99; p=0.041; Summary: Inverse: “Consistently high” DASH & CD | - Did not account for: SEP (marital status adjusted); Did not account for Δ in physical activity; - Diet assessment: FFQ assessed at baseline and screener FFQs at F/U 3 and 4; - Outcome measurement: MMSE (Singapore-modified) - CD based on SM-MMSE using education-specific cut-points: ≥18 if no education, ≥21 for primary, or ≥25 for secondary school or higher education; Funding: Agency for Science, Technology and Research; National University Health System; Singapore National Medical Research Council; NCI/NIH; Saw Swee Hock School of Public Health, National University of Singapore
Larsson & Wolk, 2018 ^36^; Sweden; Swedish Infrastructure for Medical Population-based Life-course Environmental Research (SIMPLER; Previously Swedish Mammography Cohort/Cohort of Swedish Men); Analytic N=28775; Participant characteristics:; - [underlined: Race and/or Ethnicity: NR]; - [underlined: SEP]: Post-secondary education, 8.4%; - [underlined: Selection:] Excluded those with incorrect/missing personal identity number; those who died before 1998; with hx dementia, stroke, or cancer; extreme energy intakes; below age 65 y at baseline | - DP Age(s): 71.6 y (mean); range 65–83 y; - DP(s) examined: DASH Score [Fung 2008]; - modified Mediterranean (mMED) [Larsson, 2017]; - DP Components:; - DASH, Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy. Negative: Red and Processed Meat; Sweetened Beverages (excluded Sodium); - mMED: Positive: Vegetables; Legumes and Nuts; Fruit; Whole Grains; Fish; Olive Oil; Low-Moderate Alcohol; Negative: Red and Processed Meat; Full-Fat Dairy; - DP Method(s): Index/Score; Comparisons: Categorical, quartiles | Follow-Up Duration: 12.6 y (mean); Results:; DASH & Dem; Q1, HR: 1, ref; Q2, HR: 0.96, 95% CI: 0.88, 1.06; Q3, HR: 0.94, 95% CI: 0.85, 1.03; Q4, HR: 0.96, 95% CI: 0.87, 1.05; mMED & Dem; Q1, HR: 1, ref; Q2, HR: 1.03, 95% CI: 0.88, 1.21; Q3, HR: 1.11, 95% CI: 0.95, 1.31; Q4, HR: 1.12, 95% CI: 0.96, 1.31; Summary: NS/Null: DASH & Dem; NS/Null: mMED & Dem | - Did not account for: SEP, Race and/or Ethnicity,; - Results similar when stratified by sex; - Diet assessment: FFQ once at baseline. DASH score was modified to exclude sodium since FFQ did not collect this information.; - Outcome measurement: Incident dementia identified through linkage to Swedish National Patient Register; Funding: Swedish Research Council
Liang, 2022 ^37^; China; Chinese Longitudinal Healthy Longevity Survey (CLHS); Analytic N=4792; Participant characteristics:; - [underlined: Race and/or Ethnicity: NR] (100% Chinese); - [underlined: SEP]: ∼49% Illiteracy (median); - ∼24% financial independence (median); - ∼62% agricultural, forestry, animal husbandry, or fishery worker; - [underlined: Selection:] Excluded those with missing data (BMI, cognition, diet); aged <65 y; Dx dementia or Alzheimer’s Dz at baseline; MMSE score <18 at baseline | - DP Age(s): 80.7 y (mean) at baseline; 65+ y at baseline; - DP(s) examined: Plant-Based Diet Index (PDI) [Satija, 2016]; - Healthful PDI (hPDI) [Satija, 2016]; - unhealthful PDI (uPDI) [Satija, 2016]; - DP Components:; - PDI: Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Negative: Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; - hPDI: Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Negative: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; - uPDI: Negative: Whole grains; Fruits; Vegetables; Nuts; Legumes; Vegetable oils; Tea/coffee; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; Positive: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; - DP Method(s): Index/Score; Comparisons: Categorical, lower vs. higher (median split) PDI, hPDI, uPDI (Higher, HR: 1, ref) | Follow-Up Duration: ∼3–6y; Results:; Lower vs. higher PDI, HR: 1.32, 95% CI: 1.16, 1.50, p-trend<0.001; Lower vs. higher hPDI, HR: 1.46, 95% CI: 1.29, 1.66, p-trend<0.001; Lower vs. higher uPDI, HR: 1.21, 95% CI: 1.21, 95% CI: 1.06, 1.38, p-trend=0.004; Summary: Inverse: PDI & cognitive impairment; Inverse: hPDI & cognitive impairment; Positive: uPDI & cognitive impairment | - Did not account for: Anthropometry (stratified analyses by BMI-status),; - Race and/or Ethnicity (100% Chinese); - Diet assessment: FFQ assessed once at baseline; - Outcome measurement: MMSE (Chinese version); Funding:
Liu, 2022 ^38^; United States; Chicago Health and Aging Project (CHAP); Analytic N=3337; Participant characteristics:; - [underlined: Race and/or Ethnicity]:60% ‘African-Amercian’; 40% White; - [underlined: SEP]: Education, 12.9y mean {SD: 3.41); - [underlined: Selection:] Excluded those with missing ApoE measure (n=1416), or FFQ (n=3791); <2 cognitive assessments (n=1174); implausible/extreme BMI or TEI; aged <65 y | - DP Age(s): ∼73.7y (SD: 5.72); ≥65y at baseline; - DP(s) examined: Plant-based diet index (PDI; healthful/unhealthful) [Satija, 2016]; - DP Components:; - PDI: Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Negative: Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; - hPDI: Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Negative: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; - uPDI: Negative: Whole grains; Fruits; Vegetables; Nuts; Legumes; Tea/coffee; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; Positive: Fruit juices & Veg. Oils; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; - DP Method(s): Index/Score; Comparisons: Categorical, quartiles (Q1 ref) of PDI, hPDI, uPDI | Follow-Up Duration: NR; Results:; PDI & CD, p ± SE; Black; Q2; 0.0052 ± 0.0076; Q3; 0.0039 ± 0.0068; Q4; −0.0014 ± 0.0076; Q5; 0.0072 ± 0.0073; P-trend= 0.51; White; Q2; 0.0105 ± 0.0099; Q3; −0.0005 ± 0.0091; Q4; −0.0037 ± 0.0097; Q5; 0.0010 ± 0.0095; P-trend= 0.24; hPDI, p ± SE; Black; Q2; 0.0086 ± 0.0084; Q3; 0.0167 ± 0.0084; Q4; 0.0175 ± 0.0082; Q5; 0.0183 ± 0.0086; P-trend= 0.04; White; Q2; −0.0106 ± 0.0084; Q3; −0.0053 ± 0.0093; Q4; −0.0031 ± 0.0088; Q5; −0.0047 ± 0.0098; P-trend= 0.65; uPDI & CD, β ± SE; Black; Q2; −0.0091 ± 0.0075; Q3; −0.0015 ± 0.0084; Q4; −0.0097 ± 0.0080; Q5; −0.0137 ± 0.0086; P-trend= 0.21; White; Q2; −0.0022 ± 0.0083; Q3; −0.0041 ± 0.0090; Q4; −0.0084 ± 0.0094; Q5; −0.0091 ± 0.0096; P-trend= 0.44; Summary: NS/Null: PDI & CD among Black or White participants; Inverse: higher hPDI & slower CD/slower decline in episodic memory, perceptual speed among Black participants; NS, White participants; NS/Inverse: uPDI & CD among Black or White participants | - Did not account for: SEP; Physical activity; Anthropometry; Alcohol; - n=61 new dementia cases; - Diet assessment: FFQ assessed every cycle (∼3y); - Outcome measurement: CD: global cognition score from avg. z-score of combined MMSE; East Boston (immediate; delayed); and Symbol Digit); Episodic memory avg. z-score from East Boston (immediate; delayed); Perceptual memory from z-score of Symbol Digit; Funding: NIA; NIH
Lohman, 2023 ^39^; United States; Health and Retirement Study (HRS); Analytic N=6968; Participant characteristics:; - [underlined: Race and/or Ethnicity]:16.3% Black; 7.1% Other; 76.6% White; - [underlined: SEP]: HH Income, mean: $70,000/y; Using SNAP, ∼9%; Education, mean 13y; - [underlined: Selection:] Excluded those with or who: MMSE <17 or baseline cognitive score <7, incomplete/invalid diet or outcome data, were unable to locate or lived in a nursing home | - DP Age(s): 67 (10) y; ≥51y at baseline; - DP(s) examined: Healthy Eating Index (HEI-2015) [Krebs-Smith 2018]; - DP Components:; - HEI-2015, Positive: Total Vegetables; Greens and Beans; Total Fruit; Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; PUFA+MUFA/SFA. Negative: Refined Grains; Added Sugars; SFA; Sodium; - DP Method(s): Index/Score; Comparisons: Categorical, HEI-2015 < 51 “Poor”, 51–80 “Need Improvement”, >80 “Good” quality | Follow-Up Duration: 2y, 4y, 6y, and 8y F/U; Results:; HEI-2015 & CD at; 2014 Wave β: −0.02 (−0.11, 0.08); 2016 Wave β: 0.07 (−0.03, 0.17); 2018 Wave β: 0.01 (−0.12, 0.10); 2020 Wave β: 0.17 (0.05, 0.29); Summary: Inverse: HEI-2015 & CD (2020, end of f/u); Null: HEI-2015 & CD (2014, 2016, 2018) | - Did not account for: Physical Activity, Anthropometry; - Results were similar after examining those only age 65y or older; among SNAP users; in only Black or Other vs. White Race and/or Ethnicity group; - Diet assessment: FFQ assessed once at baseline; - Outcome measurement: CD defined as TICS-m score of < 7 (alternative scale in 65y+, 0–8); Funding: None
Lu, 2021 ^40^; Japan; Ohsaki Cohort Study; Ohsaki Cohort 2006 Study; Analytic N=3146; Participant characteristics:; - [underlined: Race and/or Ethnicity: NR] (100% Japanese); - [underlined: SEP]: Education: Junior high school or lower, ∼30%; - [underlined: Selection:] Excluded those without valid response data; those who disagreed to release long-term care insurance information; those with existing disability before f/u; those with missing data | - DP Age(s): ≥65 y; ∼74 y (mean); - DP(s) examined: Japanese Dietary Index (JDI) [Abe 2019]; - DP Components:; - Positive: Seaweeds, Pickles, Green, Yellow Vegetables (green vegetables, carrot, pumpkin, tomato); Rice; Fish (rawfish, fish boiled with soy, roast fish, boiled fish paste, dried fish); Beef and Pork (beef, pork, ham, sausage); Miso Soup, Green Tea, Coffee; - DP Method(s): Index/Score; Comparisons: Categorical, by JDI change (great decrease, ≤ −2 points; moderate decrease, = 1 point; no changes, = 0 point; moderate increase (= +1 point), and great increase (≥ +2 points) | Follow-Up Duration: 5.0 years (mean); Results:; Incident Dementia; Great decrease, HR: 1.72, 95% CI: 1.13, 2.62; Moderate decrease, HR: 1.10, 95% CI: 0.73, 1.66; No change, HR: 1.00, ref; Moderate increase, HR: 0.82, 95% CI: 0.54, 1.25; Great increase, HR: 0.62, 95% CI: 0.38, 1.02; p-trend<0.0001; Summary: Inverse: Increase in JDI & decrease incident dementia; Inverse: Decrease in JDI & increase incident dementia | - Did not account for: SEP, Race and/or Ethnicity (100% Japanese),; - Results similar when excluding those with worse cognitive function at baseline; results slightly attentuated but still significant when excluding those whose dementia ascertained in first 2 yrs of f/u; - Diet assessment: FFQ assessed in 1994 and 2006; change score = 2006–1994 score; - Outcome measurement: Incident dementia defined according to long-term care insurance information; Funding: Ministry of Health, Labour and Welfare, Japan
Malek, 2022 ^41^; Malyasia; Long Term Research Grant Scheme-Towards Useful Ageing (LRGS-TUA); Analytic N=280; Participant characteristics:; - [underlined: Race and/or Ethnicity]: Malay, 56%; Chinese, 40%, Indian 4%; - [underlined: SEP]: HH income (RM), 1448±1899; 100% lower educational attainment (∼6y, mean), 58% urban; 76% married, 91% living with family; - [underlined: Selection:] Excluded those who refused to participant, unable to locate, or died | - DP Age(s): 67.3y, nean (60y+); - DP(s) examined: “Sweet foods-beverages”; - “Meat-vegetables-rice and noodles”; - “Local snacks-fish and seafoods-high-salt-foods”; - “Fruits-legumes”; - “Tropical fruits-oats”; - DP Components:; - “Sweet foods-beverages”: High intakes of sweetened creamer, granulated sugar, egg jam, and fruit jam; coffee, tea, and malted drink. Low intakes of dairy products including low fat milk and butter.; - “Meat-vegetables-rice and noodles”: Beef and pork. Vegetables: Brinjal, okra, carrot, cucumber, broccoli, long bean, chili, spinach, mustard leaves, tapioca shoots, ulam rajaa, swamp cabbage, fern shoots, mung bean, cabbage, and kale; rice porridge, white rice, dried noodle, and wet noodle; meat, including beef and pork, various types of vegetables and also rice and noodles.; - “Local snacks-fish and seafoods-high-salt-foods”: high intakes of local snacks e.g. banana fritters, cucurb, banana ball, curry puff, and cakoic; fish and seafood: pomfret, tuna, Indian mackerel, round scad, red snapper, hairtail scad, trevally, sea perch, Spanish mackerel, cuttlefish, and prawn; High salt foods: Salted fish, anchovy sauce, fermented durian, and chili shrimp paste; Malaysian snacks, fish and seafood, sauces, and condiments.; - “Fruits-legumes”: Red apple, green apple, and grapes. Legumes: Soy bean fermented cake, soy bean cake, and yellow dhal.; - “Tropical fruits-oats”: High loadings for tropical fruits: papaya, orange, banana, duku, and rambutan; Oats.; - DP Method(s): Factor/cluster; - Comparisons: Categorical, tertiles (T1, low, REF) for each DP “Sweet foods-beverages”;; - “Meat-vegetables-rice and noodles”; - “Local snacks-fish and seafoods-high-salt-foods”; - “Fruits-legumes Fruits”; “Tropical fruits-oats” | Follow-Up Duration: 5y; Results:; Each DP & odds of Dem (95% CI); Sweet foods-beverages; T2, OR: 1.086 (0.198, 5.968); p=0.924; T3, OR: 1.872 (0.325, 10.789); p=0.483; Meat-vegetables-rice and noodles; T2, OR: 4.993 (0.432, 57.662); p=0.198; T3, OR: 10.478 (0.931, 117.939); p=0.057; Local snacks-fish and seafoods-high-salt-foods; T2, OR: 0.354 (0.034, 3.661); p=0.384; T3, OR: 3.003 (0.479, 18.836); p=0.241; Fruits-legumes; T2, OR: 1.629 (0.234, 11.363); p=0.622; T3, OR: 3.852 (0.545, 27.242); p=0.177; Tropical fruits-oats; T2, OR: 0.152 (0.026, 0.871); p=0.034; T3, OR: 0.101 (0.011, 0.967); p=0.047; Each DP & odds of MCI (95% CI); Sweet foods-beverages; T2, OR: 1.576 (0.631, 3.934); p=0.330; T3, OR: 1.066 (0.329, 3.455); p=0.915; Meat-vegetables-rice and noodles; T2, OR: 0.712 (0.258, 1.966); p=0.512; T3, OR: 0.591 (0.219, 1.590); p=0.297; Local snacks-f; Summary: NS/Null: “Sweet foods-beverages” & MCI or Dem; NS/Null: “Meat-vegetables-rice and noodles” & MCI or Dem; Positive: “Local snacks-fish and seafoods-high-salt-foods” & MCI; NS/Null: Dem; NS/Null: “Fruits-legumes Fruits” & CMI or Dem & MCI or Dem; Inverse: “Tropical fruits-oats” & Dem; Ns/Null: MCI | - Did not account for: None (all) (Sex, Smoking, and Physical activity were not adjusted for in analyses and did not differ between comparison groups); - Diet assessment: Diet Hx once at baseline; - Outcome measurement: CDR scale (Clinical dementia rating) assessed by accredited researcher to Dx dementia; - MCI based on objective memory complaints (≥ 1.5SD below mean RAVLT) and subjective memory complaints but no ADL issues, no Dx of Dem, and (Malay) MMSE ≥ 19.; Funding: Ministry of Higher Education Malaysia; Grand Challenge Grant Project 1 and Project 2; Universiti Kebangsaan Malaysia
Mamalaki, 2023 ^42^; Greece; Hellenic Longitudinal Investigation of Aging and Diet (HELIAD); Analytic N=537; Participant characteristics:; - [underlined: Race and/or Ethnicity: NR] (Greek); - [underlined: SEP]: Education: 7.2 (5)y, mean; - [underlined: Selection:] Excluded those with dementia at baseline or no available genetic, dietary, or cognitive data at F/U | - DP Age(s): 73.1 (5) y; ≥65y at baseline; - DP(s) examined: Mediterranean-based Diet Score (MedDietScore) [Panagiotakos 2007]; - DP Components:; - MedDietScore, Positive: Vegetables; Potatoes; Legumes; Fruit; Whole Grains; Fish; Olive Oil. Negative: Red and Processed Meat; Poultry; Full-Fat Dairy; Alcohol (all=“Wine”); - DP Method(s): Index/Score; Comparisons: Categorical, Low MedDietScore vs. High REF (median split) | Follow-Up Duration: 2.9 (0.8)y, mean; Results:; Low vs. High (Ref) MedDietScore & Alz (Table S1 fully adjusted); Low PGI-AD, HR: 9.857, 95% CI: 1.999, 52.475; p=0.025; High PGI-AD, HR: 1.478, 95% CI: 0.356, 5.988; p=0.561; Summary: Inverse: MedDietScore & Incident Alz in those at low genetic risk for Alz; NS in those at high genetic risk for Alz | - Did not account for: SEP, Physical activity; - Only examined by genetic-risk status for Alz; - Diet assessment: FFQ assessed once at baseline; - Outcome measurement: cases of Alz, n=28; Alz based on NINCDS/ADRDA criteria; Individual cognitive test scores (e.g., MMSE; Greek VL; Complex Figure; Boston; TMT; CDT) used to produce an average domain score for memory, language, attention speed, executive, and visual–spatial functioning; Global cognitive score based on the averages of individual scores; Funding: Alzheimer’s Association; European Social Fund; Ministry of Health and Social Solidarity
Mattei, 2019 ^43^; United States; Boston Puerto Rican Health Study; Analytic N=913; Participant characteristics:; - [underlined: Race and/or Ethnicity: NR] (100% Puerto Rican); - [underlined: SEP]: Education at 8th grade or less, ∼45%–54%; - [underlined: Selection:] Excluded those with or who had: implausible TEI; incomplete cognitive evals; missing glucose values for T2D status | - DP Age(s): ∼56–59y, mean; 45–75 y at baseline; - DP(s) examined: Mediterranean Diet Score (MDS) [Trichopolou 2003]; - Healthy Eating Index (HEI-2005) [Guenther 2008]; - Alternative HEI (AHEI)-2010 [Chiuve 2012]; - DASH Score [Fung 2008]; - DP Components:; - MDS, Positive: Vegetables; Legumes; Fruit, Nuts; Cereals; Fish; MUFA/SFA. Negative: Red and Processed Meat; Dairy Products. Neutral: Alcohol; - HEI-2005, Positive: Total Vegetables; Dark Green/Orange Vegetables, Legumes; Total Fruit; Whole Fruit; Whole Grains; Total Grains; Meat and Beans; Milk, Yogurt, Cheese, and Soy Beverages; Healthy Oils. Negative: SFA; Solid fats, Alcohol, and Added Sugars; Sodium; - AHEI-2010, Positive: Vegetables (not potatoes); Fruit; Legumes and Nuts; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA. Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Trans FA; Sodium. Neutral: Alcohol; - DASH, Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Total dairy; Negative: Red and Processed Meat; Sweetened beverages; Sodium;; - DP Method(s): Index/Score; - Comparisons: Continuous, MDS; - HEI-2005; - AHEI-2010; DASH | Follow-Up Duration: ∼2y; Results:; MDS, β ± SE, in those w/ T2D (data NR for those w/o T2D); Global CFx, 0.027 ± 0.011; P=0.016; MMSE, 0.156 ± 0.072; P=0.031; Word recognition 0.365 ± 0.152; P=0.017; Figit span forward 0.106 ± 0.046; P=0.023; Clock drawing 0.066 ± 0.028; P=0.022; Data NR for other tests (NS); HEI-2005, β ± SE, in those w/o T2D; w/ T2D; Global CFx, 0.001 ± 0.001; p=0.74; 0.003 ± 0.002; p=0.18; Executive Fx, −0.287 ± 0.030; p=0.39; 0.001 ± 0.004; p=0.74; Memory Fx, 0.011 ± 0.003; p=0.002; 0.007 ± 0.005; p=0.19; MMSE, −0.012 ± 0.010; p=0.24; 0.023 ± 0.014; p=0.09; Word list learning, 0.049 ± 0.042; p=0.25; 0.012 ± 0.054; p=0.82; Word recognition, 0.063 ± 0.020; p=0.002; 0.074 ± 0.030; p=0.014; Stroop, −0.004 ± 0.039; p=0.92; −0.052 ± 0.046; p=0.26; Letter fluency, 0.002 ± 0.039; p=0.95; 0.018 ± 0.041; p=0.67; Digit span forward, −0.011 ± 0.007; p=0.11; 0.014 ± 0.009; p=0.13; Digit span backward, −0.003 ± 0.005; p=0.56; −0.016 ± 0.007; p=0.023; Clock drawing, −0.001 ± 0.003; p=0.76; 0.007 ± 0.006; p=0.2; Figure copying, 0.017 ± 0.025; p=0.5; −0.010 ± 0.031; p=0.74; AHEI-2010, β ± SE, in those w/o T2D; w/ T2D; Global CFx, 0.002 ± 0.002; p=0.25; 0.001 ± 0.002; p=0.57; Executive Fx, 0.002 ± 0.003; p=0.42; 0.002 ± 0.004; p=0.54; Memory Fx, 0.012 ± 0.004; p=0.001; 0.007 ± 0.005; p=0.17; MMSE, 0.001 ± 0.011; p=0.94; 0.003 ± 0.014; p=0.85; Word list learning, 0.066 ± 0.043; p=0.13; 0.080 ± 0.054; p=0.14; Word recognition, 0.062 ± 0.021; p=0.004; 0.033 ± 0.030; p=0.27; Stroop, 0.078 ± 0.041; p=0.06; −0.021 ± 0.045; p=0.64; Letter fluency, −0.034 ± 0.042; p=0.42; −0.019 ± 0.042; p=0.65; Digit span forward, 0.001 ± 0.007; p=0.89; 0.008 ± 0.009; p=0.36; Digit span backward, 0.002 ± 0.006; p=0.73; 0.0001 ± 0.007; p=0.98; Clock drawing, 0.002 ± 0.004; p=0.51; 0.004 ± 0.006; p=0.5; Figure copying, 0.026 ± 0.025; p=0.32; −0.040 ± 0.031; p=0.2; DASH, β ± SE, in those w/o T2D; w/ T2D; Global CFx, 0.002 ± 0.004; p=0.53; 0.002 ± 0.005; p=0.65; Executive Fx, 0.003 ± 0.006; p=0.68; −0.001 ± 0.008; p=0.9; Memory Fx, 0.024 ± 0.008; p=0.003; 0.020 ± 0.012; p=0.09; MMSE, 0.003 ± 0.024; p=0.91; 0.047 ± 0.032; p=0.14; Word list learning, 0.224 ± 0.097; p=0.021; 0.128 ± 0.119; p=0.25; Word recognition, 0.081 ± 0.048; p=0.09; 0.039 ± 0.067; p=0.56; Stroop, 0.271 ± 0.091; p=0.003; 0.029 ± 0.100; p=0.78; Letter fluency, −0.064 ± 0.092; p=0.48; −0.100 ± 0.092; p=0.28; Digit span forward, −0.012 ± 0.015; p=0.44; −0.024 ± 0.020; p=0.23; Digit span backward, 0.012 ± 0.013; p=0.34; 0.007 ± 0.016; p=0.65; Clock drawing, 0.001 ± 0.008; p=0.92; 0.006 ± 0.013; p=0.62; Figure copying, 0.059 ± 0.058; p=0.31; −0.049 ± 0.071; p=0.49; Summary: Positive: MDS if with T2D & Global CFx; MMSE; Word recognition; Digit span fwd.; Clock draw; NS/Null: Executive Fx; Memory Fx; Word list learning; Stroop; Letter fluency; Digit span back; Figure copy; Positive: HEI-2005 if w/o T2D & Memory Fx; Word Recognition; NS/Null: Global CFx; Executive Fx; MMSE; Word list or recognition; Stroop; Letter fluency; Digit span fwd. or back; Clock draw; Figure copy (Mostly NS in w/ T2D); Positive: AHEI-2010 if w/o T2D & Memory Fx; Word Recognition; NS/Null: Global CFx; Executive Fx; MMSE; Word list or recognition; Stroop; Letter fluency; Digit span fwd. or back; Clock draw; Figure copy (NS in w/ T2D); Positive: DASH if w/o T2D & Memory Fx; Word Recognition; NS/Null: Global CFx; Executive Fx; MMSE; Word list or recognition; Stroop; Letter fluency; Digit span fwd. or back; Clock draw; Figure copy (NS in w/ T2D) | - Did not account for: None (all); Alcohol not in DASH; - Primary exposure was MDS and primary outcome was CD stratified by T2D status; - Diet assessment: FFQ assessed once at baseline; - Outcome measurement: CD based on composite of z-scores from battery of CFx tests (MMSE; Stroop); Funding: NIH (NHLBI; NIA); Harvard University (Catalyst of the Harvard University Clinical and Translational Science Center)
Melo van Lent, 2021 ^44^; United States; Framingham Heart Study (FHS) Offspring Cohort; Analytic N=1584; Participant characteristics:; - [underlined: Race and/or Ethnicity: NR] (“Mainly white individuals of European ancestry”); - [underlined: SEP]: Education:; - 31.4% up to high school degree; - 29.5% some years of college; - 39.2% college degree; - [underlined: Selection:] Excluded those with extreme energy intake; >13 missing FFQ items; no cognitive data; | - DP Age(s): 61.9 y (mean); - DP(s) examined: Mediterranean-Dash Intervention for Neurodegenerative Delay diet (MIND) [Morris, 2015, modified to encompass more items]; - DP Components:; - mMIND, Positive: Green leafy vegetables; Other Vegetables; Beans; Berries; Nuts; Whole Grains; Fish (not fried); Poultry (not fried); Olive oil; Wine. Negative: Red Meat and products (e.g., bacon, hot dogs, processed meats); Cheese; Pastries and sweets; Butter and stick margarine; Fried/fast food; - DP Method(s): Index/Score; Comparisons: Continuous, per 1-pt | Follow-Up Duration: 6.6 y (mean); Results:; ΔGlobal cognition (cognitive decline); β: −0.002, SE: 0.02, p-trend=0.87; Total brain volume, β: 0.02, SE: 0.01, p-trend=0.02; Lateral Ventricular volume, β: −0.007, SE: 0.01, p-trend=0.59; Hippocampal volume, β: 0.02, SE: 0.01, p-trend=0.20; White-matter hyperintensity volume, β: −0.20, SE: 0.01, p-trend=0.15; Silent brain infarcts, OR: 0.99, 95% CI: 0.91, 1.09, p-trend=0.89; Summary: Null: MIND & cognitive decline; Positive: MIND & total brain volume; Null: MIND & other MRI markers (lateral ventricular volume, hippocampal volume, white-matter hyperintensity volume, silent brain infarcts) | - Did not account for: SEP, Race and/or Ethnicity; - Individual domains of cognition also showed no association with MIND score; - Diet assessment: FFQ assessed at least twice (cycle 7 & 5 and/or 6); 86% of sample had all 3 assessments; - Outcome measurement: Global cognitive decline: composite of visual/meaningful memory (Visual Reproductions Delayed Recall; Logical Memory Delayed Recall from the Wechsler Memory Scale); verbal comprehension/reading (Similarities from the Wechsler Adult Intelligence Scale; processing speed & EF (Trail Making Test A; Trail Making Test B minus A); closure/visual integration and mental rotation (Hooper Visual Organization Test); - Total brain volume (TBV), lateral ventricular volume (LVV), hippocampal volume (HPV)), silent brain infarcts (SBIs), and white matter injury (white matter hyperintensity volume (WMHV) assessed via MRI at cycle 7; Funding: NIH
Melo van Lent, 2022 ^45^; United States; NHS; Analytic N=16058; Participant characteristics:; - Race and/or Ethnicity: NR; primarily white; - [underlined: SEP]: Education:; - Registered nurse, ∼73–80%; - Bachelor’s degree, ∼13–19%; - Master’s or doctorate, ∼5.6–8%; - [underlined: Selection:] Excluded those with missing 1 or more FFQ; without at least 1 cognitive assessment; incomplete data for physical activity | - DP Age(s): 74 (2)y, mean (30–55y) at baseline; - DP(s) examined: Empirical dietary inflammatory pattern (EDIP) [Tabung, 2016]; - DP Components:; - Anti-inflammatory group: tea, coffee, dark yellow vegetables (carrots, or squash), leafy green vegetables (cabbage, spinach, or lettuce), snacks (cracker, or potato chips), fruit juice (apple juice, cantaloupe juice, orange juice, or other fruit juice), pizza; - Pro-inflammatory group: processed meat (sausage), red meat (beef, or lamb), organ meat (beef, calf, or chicken liver), other fish (canned tuna, or fish), other vegetables (mixed vegetables, green pepper, cooked mushroom, eggplant, zucchini, or cucumber), refined grains (white bread, biscuit, white rice, pasta, or vermicelli), high-energy and low energy beverages (cola with sugar, carbonated beverages with sugar, fruit punch drinks), and tomatoes; - DP Method(s): Index/Score; Comparisons: Categorical, quintiles | Follow-Up Duration: 6 y; Results:; Cognitive Function (mean of 4 measures); Global; Q1, β: 1, ref; Q2, β: −0.004, 95% CI: −0.03, 0.03; Q3, β: 0.01, 95% CI: −0.02, 0.04; Q4, β: −0.04, 95% CI: −0.07, −0.01; Q5, β: −0.01, 95% CI: −0.04, 0.02; p-trend=0.230; Verbal memory; Q1, β: 1, ref; Q2, β: 0.003, 95% CI: −0.03, 0.03; Q3, β: 0.02, 95% CI: −0.01, 0.05; Q4, β: −0.01, 95% CI: −0.04, 0.02; Q5, β: 0.02, 95% CI: −0.01, 0.06; p-trend=0.326; TICS; Q1, β: 1, ref; Q2, β: 0.01, 95% CI: −0.03, 0.06; Q3, β: 0.03, 95% CI: −0.02, 0.07; Q4, β: −0.03, 95% CI: −0.08, 0.02; Q5, β: −0.02, 95% CI: −0.07, 0.02; p-trend=0.124; Cognitive Decline; Global; Q1, β: 1, ref; Q2, β: −0.001, 95% CI: −0.01, 0.01; Q3, β: 0.003, 95% CI: −0.01, 0.01; Q4, β: 0.01, 95% CI: 0.001, 0.02; Q5, β: 0.01, 95% CI: −0.003, 0.01; p-trend=0.036; Verbal memory; Q1, β: 1, ref; Q2, β: −0.002, 95% CI: −0.01, 0.01; Q3, β: 0.004, 95% CI: −0.01, 0.01; Q4, β: 0.01, 95% CI: 0.004, 0.02; Q5, β: 0.01, 95% CI: −0.002, 0.02; p-trend=0.008; TICS; Q1, β: 1, ref; Q2, β: 0.01, 95% CI: −0.002, 0.02; Q3, β: 0.01, 95% CI: −0.01, 0.02; Q4, β: 0.01, 95% CI: −0.004, 0.02; Q5, β: 0.01, 95% CI: −0.01, 0.02; p-trend=0.542; Summary: Inverse: Higher EDIP & less CD (Global, verbal memory); NS/Null: CD (TICS) or Cognitive function (mean of repeated measures) | - Did not account for: SEP, Race and/or Ethnicity (mostly white), Alcohol; - Mean age 74 at first cognitive exam; - Diet assessment: FFQ (once or twice); - Outcome measurement: TICS (Telephone Interview for Cognitive Status) including 10-word list for delayed recall; EBMT (East Boston Memory Test) for immediate & delayed recalls; category fluency; digit span backward test.; Funding: NCI, NIH
Milte, 2019 ^46^; Australia; Wellbeing, Eating and Exercise for a Long Life (WELL) study; Analytic N=617; Participant characteristics:; - [underlined: Race and/or Ethnicity: NR]; - Country of birth:; - Australia, 76.5%; - UK: 7.94%; - Other, 15.5%; - [underlined: SEP]: Education: University degree, 45%; Up to 10 y, 22%; 12 y/trade/certificate: 33%; - Retired: 35%; - Urban: 97%; - Married: 77%; Separated 13%; - [underlined: Selection:] Excluded those missing >10% responses on FFQ, one or more responses to dietary habits questions, TICS-m score or covariates. | - DP Age(s): 55–65y at baseline; mean 60.2 y; - DP(s) examined: Dietary Guideline Index - Australia (DGI-2013) [NHMRC, 2013]; - DP Components:; - DGI, 2013, Positive: Vegetables; Fruit; Grain (cereal) foods, mostly whole grain or high fibre; Lean meat and poultry, fish, eggs, nuts and seeds, and legumes/beans; Milk, yogurt, cheese, and/or their alternatives; Fluids (excluding soft drinks, cordial, fruit drinks, flavored milks, or alcoholic beverages); Variety. Negative: Discretionary foods; Saturated fat (including whole milk); Unsaturated spreads and oils; Added salt; Added sugars; Alcohol; - DP Method(s): Index/Score; Comparisons: Continuous, per 1-pt | Follow-Up Duration: 4 y; Results:; TICS-m score (linear); Per 1-pt, β: 0.00, 95% CI: −0.01, 0.03; Summary: Null: DGI-2013 & cognitive function | - Did not account for: Race and/or Ethnicity, Anthropometry, Smoking; - Analyses looked at linear relationship between DGI-2013 & TICS-m to assess cognitive function but did not look by cutoff values to assess cognitive impairment, dementia; results similar for men and women separately, and when excluding participants with CV; - Diet assessment: FFQ assessed once at baseline; - Outcome measurement: TICS-m; ≥32=normal cog function, 28–31=mild cog impairment, ≤ 27=dementia; Funding: Medibank Health Research Fund, Diabetes Australia Research Trust, Australian Research Council
Morris, 2015 ^47^; United States; Rush Memory and Aging Project (MAP); Analytic N=960; Participant characteristics:; - [underlined: Race and/or Ethnicity]:95% white; 98.5% non-Hispanic; - [underlined: SEP]: Education level, 14.9 y (mean); - [underlined: Selection:] Excluded those w dementia at baseline; those who died or withdrew | - DP Age(s): ≥65 y at baseline; 81.4 [7.2] y (mean); - DP(s) examined: Mediterranean-Dash Intervention for Neurodegenerative Delay diet (MIND) [Morris, 2015]; - DP Components:; - Positive: Green leafy vegetables; Vegetables; Beans; Berries; Nuts; Whole Grains; Seafood; Poultry; Olive oil; Wine. Negative: Red Meat; Cheese; Pastries and sweets; Butter and stick margarine; Fried/fast food; - DP Method(s): Index/Score; - Comparisons: Continuous, per pt; Categorical, tertiles | Follow-Up Duration: 4.7y (mean); Results:; Global cognition, β (SE); Linear, 0.0106 (0.0023); p-trend<0.0001; T3, 0.0366 (0.0101), p-trend=0.003; T2, 0.0243 (0.0099), p-trend=0.01; Episodic memory, β (SE); Linear, 0.0090 (0.0028); p-trend=0.001; Semantic Memory, β (SE); Linear, 0.0113 (0.0027); p-trend<0.0001; Pereptual Organization, β (SE); Linear, 0.0077 (0.0025); p-trend=0.002; Perceptual Speed, β (SE); Linear, 0.0097 (0.0023); p-trend<0.0001; Working memory, β (SE); Linear, 0.0060 (0.0024); p-trend=0.01; Summary: Inverse: MIND score (cont. & categorical) & (less decline/rate of change in) global cognition; Inverse: MIND score (cont.) & (less decline/rate of change in) episodic memory, semantic memory, perceptual organization, perceptual speed, working memory | - Did not account for: SEP, Anthropometry (BMI across tertiles: 27.5, 27.1, 26.7); - Primarily female (75%); separate model incorporating low weight (BMI≤20) and obesity (BMI≥30) found “there was no statistical evidence that the diet effect on the global or individual domain cognitive scores differed by level or presence of” these variab; - Diet assessment: FFQ assessed at each annual visit but baseline only used after testing change (very small); - Outcome measurement: MMSE; Annual structured clinical evaluations including cognitive testing by technicians (trained & certified); 52% of sample had 5+ cognitive assessments; Funding: NIA
Morris, 2015 ^48^; United States; Rush Memory and Aging Project (MAP); Analytic N=789; Participant characteristics:; - [underlined: Race and/or Ethnicity: NR]; - (likely similar to Morris, 2015_slows, which is primarily non-Hispanic White); - [underlined: SEP]: Mean years of education, ∼14.3–15.6y; - [underlined: Selection:] Excluded those w dementia at baseline; those who died or withdrew | - DP Age(s): ∼81.4 y (mean); ≥65 y at baseline; - DP(s) examined: Mediterranean-Dash Intervention for Neurodegenerative Delay diet (MIND) [Morris, 2015]; - Mediterranean-based Diet Score (MedDietScore) [Panagiotakos 2007]; - DASH diet score [Folsom, 2007]; - DP Components:; - MIND: Positive: Green leafy vegetables; Vegetables; Beans; Berries; Nuts; Whole Grains; Seafood; Poultry; Olive oil; Wine. Negative: Red Meat; Cheese; Pastries and sweets; Butter and stick margarine; Fried/fast food; - MedDietScore: Positive: Vegetables; Potatoes; Legumes; Fruit; Whole Grains; Fish; Olive Oil. Negative: Red and Processed Meat; Poultry; Full-Fat Dairy; Alcohol; - DASH: Positive: Vegetables; Nuts and Legumes; Fruit; Total Grains; Low-Fat Dairy; Negative: Fish; Meat; Poultry; Sweets; Total fat; Saturated fat; Sodium;; - DP Method(s): Index/Score; - Comparisons: Categorical, tertiles; Continuous, per pt | Follow-Up Duration: 4.5 y; Results:; MIND, HR (95% CI); T1, HR: 1, ref; T2, HR: 0.64 (0.42, 0.97); T3, HR: 0.48 (0.29, 0.79); p-trend (linear)=0.003; DASH; T1, HR: 1, ref; T2, HR: 0.98 (0.64, 1.46); T3, HR: 0.60 (0.37, 0.96); p-trend (linear)=0.06; MedDietScore; T1, HR: 1, ref; T2, HR: 0.81 (0.53, 1.21); T3, HR: 0.49 (0.29, 0.85); p-trend (linear)=0.01; Summary: Inverse: MIND, MedDietScore & Alz; NS/Inverse: DASH & Alz | - Did not account for: SEP, Anthropometry, Race and/or Ethnicity, Smoking; - Primarily female (∼74–78%); - Diet assessment: FFQ assessed once at baseline; - Outcome measurement: Alzheimer’s disease Dx by an experienced clinician using data from a structured neurological examination and medical history, cognitive performance testing, and with the assistance of an algorithmically-based rating of cognitive impairment. Dx criteria based on National Institute of Neurological and Communicative Disorders and Stroke and the Alzheimer’s Disease and Related Disorders Association; Funding: NIA/NIH
Moustafa, 2022 ^49^; United States; Hispanic Community Health Study/Study of Latinos (HCHS/SOL); Analytic N=6321; Participant characteristics:; - [underlined: Race and/or Ethnicity]:100% Hispanic/Latino (living in US); - US-born, 4–14%; - [underlined: SEP]: Household income:; - <$20,000, ∼43–47%; - 20,000–50,000, ∼32–38%; - >50,000, ∼9–13%; - NR, ∼6–10%; - Education level:; - <High school, ∼35–44%; - High school, ∼39–41%; - >High school, ∼39–43%; - Health insurance (yes), ∼52–63%; - [underlined: Selection:] Included those with at least 1 24-hr dietary recall at baseline; | - DP Age(s): 56.1 y (mean); 18–74 y at baseline (those over 45 y oversampled); - DP(s) examined: Mediterranean Diet Score (MDS) [Trichopolou 2003]; - modified MDS (mMDS) [Mattei 2007]; - DP Components:; - MDS: Positive: Vegetables; Legumes; Fruit, Nuts; Cereals; Fish; MUFA/SFA. Negative: Red and Processed Meat; Dairy Products. Neutral: Alcohol; - mMDS: Positive: Vegetables; Legumes; Fruit, Nuts; Whole grains; Fish; MUFA/SFA. Negative: Red and Processed Meat; Dairy Products. Neutral: Alcohol; - DP Method(s): Index/Score; Comparisons: Categorical, low (0–4pts), medium (5–6pts), high (7–9pts) | Follow-Up Duration: 7 y; Results:; MDS & ΔGlobal cognition; Low, mean: 0.01, 95% CI: −0.008, 0.10; Moderate, mean: 0.03, 95% CI: −0.06, 0.12; High, mean: 0.05, 95% CI: −0.05, 0.15; p-trend=0.32; Low vs. moderate, mean difference: 0.02, 95% CI: −0.02, 0.06; Low vs. high, mean difference: 0.04, 95% CI: −0.01, 0.09; mMDS & ΔGlobal cognition; Low, mean: 0.01, 95% CI: −0.008, 0.10; Moderate, mean: 0.04, 95% CI: −0.05, 0.13; High, mean: 0.04, 95% CI: −0.06, 0.14; p-trend=0.25; Low vs. moderate, mean difference: 0.03, 95% CI: −0.01, 0.07; Low vs. high, mean difference: 0.03, 95% CI: −0.02, 0.08; Summary: Null: MDS, mMDS & ΔGlobal cognition | - Did not account for: None (all); - Diet assessment: Diet recall once at baseline; - Outcome measurement: Learning (Brief Spanish-English Verbal Learning Test (B-SEVLT) Sum, which includes 3 learning trials; B-SEVLT Recall, a delayed verbal episodic and memory trial; word fluency (verbal) for speech production; Digit Symbol Substitution Test (DSST) for sustained attention, psychomotor speed, and executive function; Funding: NIH (NIA & NHLBI)
Mueller, 2020 ^50^; United States; Wisconsin Registry for Alzheimer’s Prevention (WRAP); Analytic N=828; Participant characteristics:; - [underlined: Race and/or Ethnicity]:98.2% non-Hispanic White; - [underlined: SEP]: 16.2 y education (mean); - [underlined: Selection:] All free of dementia at baseline. Excluded those with <2 visits; with MCI at baseline; with Hx stroke, Parkinson’s Dz, MS, epilepsy; without complete data on diet, PA, cognitive activities | - DP Age(s): 53.7y (mean) at baseline; - DP(s) examined: Mediterranean-Dash Intervention for Neurodegenerative Delay diet (MIND) [Morris, 2015]; - DP Components:; - MIND, Positive: Green leafy vegetables; Vegetables; Beans; Berries; Nuts; Whole Grains; Seafood; Poultry; Olive oil; Wine. Negative: Red Meat; Cheese; Pastries and sweets; Butter and stick margarine; Fried/fast food; - DP Method(s): Index/Score; Comparisons: Continuous | Follow-Up Duration: 6.3 (1.9) y, mean (7y median; range: 2–10); Results:; MIND & PACC4 (global cognition); Model average β: 0.018, 95% CI: −0.66, 0.54; MIND & Executive Function; Model average β: −0.252, 95% CI: −1.04, −0.02; Immediate memory, NS, data NR; Delayed memory, NS, data NR; Summary: Null: MIND & PACC-4, EF, immediate & delayed memory | - Did not account for: SEP, Physical Activity, Anthropometry, Smoking; - Significant age * MIND interaction reported: those w/ greater MIND adherence showed slower decline in EFx over time; no main effect of diet. Participants were relatively young at both diet assessment (∼57y) and outcome assessment (65y), so it is possible; - Diet assessment: 15-item FFQ to assess MIND diet adherence; - Outcome measurement: Global function similar to PACC4 (Preclinical Alzheimer’s Cognitive Composite 4)- composite score of available measures: MMSE, RAVLT, WMS-R, and WAIS-R; secondary outcomes of domain-specific cognitive tests: immediate recall, delayed recall, executive function; Funding: NIH
Muhoz-Garcia, 2020 ^52^; Spain; SUN; Analytic N=806; Participant characteristics:; - [underlined: Race and/or Ethnicity: NR] (Spanish); - [underlined: SEP]: All 5–6 y university education; - [underlined: Selection:] Excluded those with missing 6-y STICS-m or saliva or implausible TEI | - DP Age(s): 66–68y across DP extremes; ≥55 y at study baseline; - DP(s) examined: Mediterranean Diet Adherence Screener (MEDAS) [Schroder 2011]; - Mediterranean Diet Score (MDS) [Trichopolou 2003]; - DASH Score [Fung 2008]; - Mediterranean-Dash Intervention for Neurodegenerative Delay diet (MIND) [Morris, 2015]; - Alternative HEI (AHEI)-2010 [Chiu; - DP Components:; - MEDAS, Positive: Vegetables; Pulses; Fruit; Nuts; Fish; White Meat Over Red Meat; Olive Oil; Olive Oil as Principal Cooking Fat; Red Wine; Sofritas (dishes with tomato, garlic, onion, leek, olive oil). Negative: Commercial Pastries; Red Meat or Sausages; Animal fat; Sugar-Sweetened Beverages; - MDS, Positive: Vegetables; Legumes; Fruit, Nuts; Cereals; Fish; MUFA/SFA. Negative: Red and Processed Meat; Dairy Products. Neutral: Alcohol; - DASH, Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Total dairy; Negative: Red and Processed Meat; Sweetened beverages; Sodium;; - MIND, Positive: Green leafy vegetables; Vegetables; Beans; Berries; Nuts; Whole Grains; Seafood; Poultry; Olive oil; Wine. Negative: Red Meat; Cheese; Pastries and sweets; Butter and stick margarine; Fried/fast food; - AHEI-2010, Positive: Vegetables (not potatoes); Fruit; Legumes and Nuts; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA. Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Trans FA; Sodium. Neutral: Alcohol; - Pro-veg, Positive: Vegetables; Potatoes; Legumes; Fruit; Nuts; Cereals; (no data on olive oil). Negative: Fish and Other Seafood; Meats and Meat Products; Eggs; Dairy Products; Animal Fats; - DP Method(s): Index/Score; Comparisons: Categorically (quintiles; tertiles; medium/moderate or high vs. Q1/T1/Low (β: 0 as REF); linear trend; Continuous, per pts of each MDS, MEDAS, DASH, MIND, AHEI-2010, Pro-veg | Follow-Up Duration: 6y, mean to 1st cognitive eval; Results:; STICS-m scores β (95% CI); MEDAS; Med., 0.28 (−0.25, 0.80);; High, 0.43 (−0.40, 1.26); p-trend=0.28; per 2pt, 0.15 (−0.08, 0.40); MDS; Med., 0.23 (−0.24, 0.69);; High, 0.32 (−0.23, 0.88); p-trend=0.26; per 1.5pt, 0.05 (−0.13, 0.23); DASH; Q2, −0.01 (−0.63, 0.60);; Q3, −0.23 (−0.84, 0.38);; Q4, −0.07 (−0.72, 0.58);; Q5, 0.30 (−0.35, 0.96); p-trend=0.43; per 5pt, 0.11 (−0.10, 0.32); MIND; T2, 0.17 (−0.28, 0.62); T3, 0.47 (−0.07, 1.02); p-trend=0.09; per 1.5pt, 0.27 (0.05, 0.48); AHEI-2010; Q2, 0.43 (−0.18, 1.04);; Q3, 0.42 (−0.23, 1.07);; Q4, 0.30 (−0.33, 0.93);; Q5, 0.81 (0.17, 1.45); p-trend=0.03; per 9pt, 0.25 (0.04, 0.45); Pro-Veg; Very Low, −0.19 (−0.87, 0.48);; Low, −0.09 (−0.74, 0.56);; Mod., 0.22 (−0.49, 0.93);; High, 0.41 (−0.56, 1.38); p-trend=0.22; per 6pt, 0.19 (−0.03, 0.40); Summary: NS/Null: MDS & STICS-m; NS/Null: MEDAS & STICS-m; NS/Null: DASH & STICS-m; Positive: MIND (per 1.5 pt) & STICS-m (NS/Positive: T2, T3 vs. T1); Positive: AHEI-2010 & STICS-m; NS/Null: Pro-veg & STICS-m | - Did not account for: SEP; Race and/or Ethnicity (Spanish); - Diet assessment: FFQ assessed repeatedly; but only baseline used for DP; - Outcome measurement: modified Spanish Telephone Interview for Cognitive Status, STICS-m; Funding: Spanish Government-Instituto de Salud Carlos III, European Regional Development Fund, Navarra Regional Government, University of Navarra
Muhoz-Garcia, 2022 ^51^; Spain; SUN; Analytic N=806; Participant characteristics:; - [underlined: Race and/or Ethnicity: NR] (Spanish); - [underlined: SEP]: All 5–6 y university education; - [underlined: Selection:] Excluded those with missing 6-y STICS-m or saliva or implausible TEI | - DP Age(s): ∼67y across DP tertiles; ≥55 y at study baseline; - DP(s) examined: Western, WDP; - Mediterranean, MDP; - DP Components:; - Western, WDP: positive loadings for refined cereals; whole-fat dairy products; eggs; sweets (cookies, cakes, nougat, chocolate, and marzipan); sugar sweetened beverages; commercial bakery; sauces; red meat; processed/precooked meat; processed red meat; fast food; - Mediterranean, MDP: positive loadings for vegetables, fruit, nuts, fish, olive oil, natural fruit juices, and other fruits (canned, dried, avocado, olives).; - DP Method(s): Factor/Cluster; Comparisons: Categorical, tertiles (T1 ref) | Follow-Up Duration: 6y, mean; Results:; STICS-m scores, Adj. differences (95% CI); WDP; T2, −0.49 (−1.03, 0.05); T3, −0.80 (−1.51,−0.08); p-trend=0.03; MDP; T2, 0.16 (−0.34, 0.66); T3, 0.71 (0.15, 1.26); p-trend=0.01; Summary: Positive: MDP & STICS-m; Inverse: WDP & STICS-m | - Did not account for: SEP; Race and/or Ethnicity (Spanish); - Diet assessment: FFQ assessed repeatedly; but only baseline used for DP; - Outcome measurement: modified Spanish Telephone Interview for Cognitive Status, STICS-m; Funding: Spanish Government-Instituto de Salud Carlos III, European Regional Development Fund, Navarra Regional Government, University of Navarra
Nicoli, 2021 ^53^; Italy; Monzino 80-plus study; Analytic N=512; Participant characteristics:; - [underlined: Race and/or Ethnicity: NR]; - [underlined: SEP]: Education, mean ∼5 y; - 90–93% living at home; - [underlined: Selection:] Participants 80+ years in Varese province, Italy; Excluded those with no FFQ data; with dementia at baseline; those lost to f/u | - DP Age(s): ∼92 y; 80+ y at enrollment; - Mean age at baseline:; - 80–84y, ∼7%; - 85–89y, ∼33%; - 90–94y, ∼27%; - 95–99y, ∼19%; - 100+y, ∼12%; - DP(s) examined: Mediterranean Diet Score (MDS) [Trichopolou 2003]; - DP Components:; - MDS, Positive: Vegetables; Legumes; Fruit, Nuts; Cereals; Fish; MUFA/SFA. Negative: Red and Processed Meat; Dairy Products. Neutral: Alcohol; - DP Method(s): Index/Score; Comparisons: Categorical, tertiles | Follow-Up Duration: 3.6 y (mean); 2.8 y (median); 12y (total); Results:; T1, HR: 1, ref; T2, HR: 1.17, 95% CI: 0.82, 1.66; T3, HR: 1.20, 95% CI: 0.82, 1.76; p-trend=0.369; Summary: NS/Positive: MDS & incident Dementia | - Did not account for: SEP, Race and/or Ethnicity,; - “Re-performed” the analyses including BMI in the fully-adjusted model” led to similar results but data NR. Baseline for these analyses in 2005 when FFQ collected; participants were enrolled prior.; - Diet assessment: FFQ once at baseline (2005); - Outcome measurement: MMSE (imputation used when MMSE n/a): incident cases of dementia identified by team of a neurologist, neuropsychologist, and psychologist using DSM-IV criteria; Funding: Italo Monzino Foundation, Milano, Italy
Nishi, 2021 ^54^; Spain; PREDIMED-Plus secondary analysis; Analytic N=6647; Participant characteristics:; - [underlined: Race and/or Ethnicity: NR] (100% Spanish); - [underlined: SEP]: Education: 49% primary; 29% high school; 22% college; 77% Married; - [underlined: Selection:] Excluded those with or who: missing dietary data at baseline and follow-up or outcome data | - DP Age(s): 65y, mean (55 to 75y at baseine); - DP(s) examined: Mediterranean Diet Adherence Screener (MEDAS) [Schroder 2011]; - DASH Score [Fung 2008]; - Mediterranean-Dash Intervention for Neurodegenerative Delay diet (MIND) [Morris, 2015]; - DP Components:; - MEDAS, Positive: Vegetables; Pulses; Fruit; Nuts; Fish; White Meat Over Red Meat; Olive Oil; Olive Oil as Principal Cooking Fat; Red Wine; Sofritas (dishes with tomato, garlic, onion, leek, olive oil). Negative: Commercial Pastries; Red Meat or Sausages; Animal fat; Sugar-Sweetened Beverages; - DASH, Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Total dairy; Negative: Red and Processed Meat; Sweetened beverages; Sodium;; - MIND, Positive: Green leafy vegetables; Vegetables; Beans; Berries; Nuts; Whole Grains; Seafood; Poultry; Olive oil; Wine. Negative: Red Meat; Cheese; Pastries and sweets; Butter and stick margarine; Fried/fast food; - DP Method(s): Index/Score; Comparisons: Categorical (Low, Ref) and linear trend for each DP (MEDAS; MIND; DASH) | Follow-Up Duration: 2y; Results:; MEDAS & GCFx, β (95% CI); Mod, 0.031 (−0.005, 0.067); High, 0.033 (−0.009, 0.075); p-trend=0.095; MEDAS & MMSE; Mod, 0.053 (0.002, 0.104); High, 0.068 (0.017, 0.125); p-trend=0.014; MEDAS & CDT; Mod, −0.015 (−0.071, 0.040); High, 0.011 (−0.052, 0.074); p-trend=0.808; DASH & GCFx; Mod, −0.042 (−0.080, −0.004); High, −0.027 (−0.067, 0.014); p-trend=0.154; DASH & MMSE; Mod, 0.013 (−0.039, 0.065); High, −0.002 (−0.058, 0.054); p-trend=0.941; DASH & CDT; Mod, −0.026 (−0.085, 0.032); High, −0.029 (−0.090, 0.032); p-trend=0.351; MIND & GCFx; Mod, −0.020 (−0.057, 0.016); High, 0.023 (−0.017, 0.063); p-trend=0.367; MIND & MMSE; Mod, 0.044 (−0.007, 0.095); High, 0.039 (−0.014, 0.092); p-trend=0.139; MIND & CDT; Mod, 0.002 (−0.056, 0.060); High, 0.030 (−0.030, 0.090); p-trend=0.329; Additional results reported for trail-making test part A and B, verbal fluency tasks (semantic; phonologic), and digit-span forward and backward; Summary: Positive: MEDAS & MMSE; Inverse: MEDAS & TMT-A or TMT-B; NS: GCFx; CDT; DST; VFT NS/Null: MIND & all (GCFx; MMSE; CDT; TMT; DST; VFT); Positive: DASH & TMT-A; NS/Null: GCFx; CDT; TMT; DST; VFT | - Did not account for: Race and/or Ethnicity (Spanish), SEP (marital status); - Indirect: primary intent of trial was weight loss and CVD-prevention; - Diet assessment: FFQ once at baseline; - Outcome measurement: CD based on cognitive battery of tests [Global cognitive function, GCFx; MMSE; Clock drawing test (CDT); Trail Making (TMT A and B); Digit Span (DST-F; DST-B); Verbal fluency tests (VFT-a; VFT-p]; Funding: Spanish Institutions for funding scientific biomedical research, CIBER Fisiopatología de la Obesidad y Nutrición (CIBEROBN) and Instituto de Salud Carlos III (ISCIII), through the Fondo de Investigación parala Salud (FIS), which was co-funded by the European Regional Development Fund; Especial Action Project
Nooyens, 2021 ^55^; The Netherlands; Doetinchem Cohort Study; Analytic N=3644; Participant characteristics:; - [underlined: Race and/or Ethnicity: NR] (Dutch); - [underlined: SEP]: Education: 23–41% Low; Married: 83–84%; - [underlined: Selection:] Excluded those with <1 diet/CD assessment | - DP Age(s): 56y, mean; 45 to 75y at baseline; - DP(s) examined: modified Mediterranean Diet Score (mMDS) [Trichopolou 2005 modified Trichopolou 2003]; - modified DHD15-index (mDHD15), Looman, 2017); excluded sodium, coffee; - DP Components:; - mMDS, Positive: Vegetables; Legumes; Fruit; Cereals; Fish; MUFA+PUFA/SFA. Negative: Meat; Dairy Products. Neutral: Alcohol; - mDHD-15, Positive: Vegetables; Legumes; Fruit; Nuts; Whole Grains; Fish; Dairy Products; Tea. Negative: Fats and Oils; Red Meat; Processed Meat; Sweetened Beverages; Fruit juices; Alcohol; - DP Method(s): Index/Score; Comparisons: Categorical, tertiles | Follow-Up Duration: 20y total (5y intervals); Results:; mean diff. (95% CI); mMDS, T3 v. T1 &; CD based on CFx, 7.4% (1.0, 14.9); CD based on Processing, 9.5% (2.1, 18.4); Global CFx, 2.0 (0.8, 3.4); change β: 0.00 (0.00, 0.01); Memory, 2.3 (0.7, 3.9); Processing, 1.7 (0.3, 3.4); Cog. Flexibility, 1.1 (0.0, 2.2); mDHD15, T3 v. T1 &; CD based on CFx, 6.5% (0.6, 13.6); CD based on Processing, 12.4% (5.5, 20.8); CD based on Cog. Flexibility, 10.3% (3.7, 18.3); Global CFx, 2.0 (0.8, 3.4); change p: 0.00 (−0.00, 0.01); Memory, 2.3 (0.7, 3.9); Processing, 1.7 (0.3, 3.4); Cog. Flexibility, 1.1 (0.0, 2.2); Summary: Inverse: mMDS & CD (NR: Memory, Cognitive flexibility); Inverse: mDHD15 & CD (NR: Memory) | - Did not account for: Race and/or Ethnicity but all Dutch, SEP but did adjust for marital status; - Sensitivity analyses by excluding lowest 2.5% global CF, those who had a CVA, or those who only had baseline cognitive eval. showed similar associations; - Diet assessment: FFQ assessed once at baseline; - Outcome measurement: Cognitive function, CF (Stroop; 15-word verbal learning (VLT); Animal naming fluency; Letter-digit); Memory (VLT; Animal naming fluency); Processing speed (Letter-digit; Stroop); Cognitive flexibility (Stroop)); Funding: Ministry of Health, Welfare and Sport of The Netherlands and the National Institute for Public Health and the Environment
Olsson, 2015 ^56^; Sweden; Uppsala Longitudinal Study of Adult Men (ULSAM); Analytic N=1038; Participant characteristics:; - [underlined: Race and/or Ethnicity: NR] (Swedish); - [underlined: SEP]: Single household, 16%; - Low educational attainment, 56%; - [underlined: Selection:] Excluded those with T2D before baseline; extreme energy intake; dementia Dx before baseline; weight loss >10% between 60–70 yrs old | - DP Age(s): 71 y (mean); - DP(s) examined: Mediterranean Diet Score (MDS) [Trichopolou 2003]; - DP Components:; - MDS: Positive: Vegetables; Legumes; Fruit, Nuts; Cereals; Fish; MUFA/SFA. Negative: Red and Processed Meat; Dairy Products. Neutral: Alcohol; - DP Method(s): Index/Score; - Comparisons: Categorical, tertiles (medium, high vs. low HR: 1 REF); - Continuous, per 1 SD | Follow-Up Duration: ∼13 y (12–14y); Results:; MDS & Dementia (all-type); Per SD, HR: 0.94, 95% CI: 0.75, 1.18; Low, HR: 1, ref; Medium, HR: 1.05, 95% CI: 0.67, 1.66; High, HR: 0.85, 95% CI: 0.44, 1.62; p-trend=0.70; MDS & Alzheimer’s Dz; Per SD, HR: 1.00, 95% CI: 0.75, 1.33; Low, HR: 1, ref; Medium, HR: 1.16, 95% CI: 0.64, 2.10; High, HR: 0.99, 95% CI: 0.44, 2.26; p-trend=0.95; MDS & Cognitive impairment (all-type); Per SD, OR: 0.82, 95% CI: 0.65, 1.05; Low, OR: 1, ref; Medium, OR: 1.32, 95% CI: 0.82, 2.15; High, OR: 0.64, 95% CI: 0.31, 1.30; p-trend=0.41; Summary: NS/Null: MDS & Alzheimer’s Dz, Dementia, Cognitive impairment | - Did not account for: SEP, Anthropometry, Race and/or Ethnicity, Alcohol (HDI); - Data were reported by authors but not included in this review for mHDI score, which only has 2 food groups (fish and combined fruits with veg) and a LCHP (low-carb/high-protein) score, which was not based on food groups only g/d of macronutrients; - Diet assessment: 7-day food record once at baseline; - Outcome measurement: MMSE for cognitive impairment (defined as all-type dementia and/or≥3 points decline in MMSE over the 12-y period and/or MMSE <25 points at follow up). Dementia & cognitive impairment: primary care & nursing home records. AD defined according to National Institute of Neurological and Communication Disorders and Stroke-Alzheimer’s Disease and Related Disorders Association criteria (NINCDS-ADRDA) & the Diagnostic and Statistical DSM-IV criteria; Funding: Swedish Research Council, The Foundation Tornspiran, The Swedish Dementia Association
Parrott, 2021 ^57^; Canada; Quebec Longitudinal Study on Nutrition and Successful Aging (NuAge): Nutrition and Cognition Substudy; Analytic N=350; Participant characteristics:; - [underlined: Race and/or Ethnicity: NR]; - [underlined: SEP]: NR; - [underlined: Selection:] Included those with MMSE score >85 at baseline; complete dietary data; free of self-reported health conditions that could impair cognition | - DP Age(s): ∼73 y (mean); 67–84 y at baseline; - DP(s) examined: n/a; - DP Components:; - “Prudent”: Positive: vegetables, salad dressing, fruits, legumes, nuts and seeds, whole-grain bread, fish and seafood, poultry, and lower-fat dairy; - “Western”: red and processed meats, white bread, potatoes, sugary drinks, candy, butter, and baked goods; - DP Method(s): Factor/Cluster; Comparisons: Continuous | Follow-Up Duration: 3.0 y (mean); Results:; “Western” DP &; Global cognition, β: −0.16, SE: 0.06, p-trend=0.009; Executive function, β: −0.60, SE: 0.27, p-trend= 0.027; Episodic memory, β: −0.02, SE: 0.05, p-trend= 0.705; “Prudent” DP:; Global cognition, β: −0.06, SE: 0.06, p-trend=0.339; Executive function, β: −0.01, SE: 0.27, p-trend= 984; Episodic memory, β: 0.01, SE: 0.05, p-trend= 0.819; Summary: Positive: Western & (faster) rate of CD (global cognition, executive function); NS/Null: Decline of episodic memory; Null: Prudent & rate of CD (global cognition, executive function, episodic memory) | - Did not account for: Race and/or Ethnicity; - Based on embedded subsample who underwent additional cognitive testing (Nutrition and Cognition Substudy); - Diet assessment: FFQ assessed once at baseline; DPs derived via PCA; - Outcome measurement: MMSE (Global cognition) assessed three times during f/u, annually. Verbal episodic memory: RL/RI-16 Free and Cued Recall Task. Executive function: Stroop task; Funding: Canadian Institutes of Health Research
Razquin, 2022 ^58^; Spain; SUN Project (sub-study); Analytic N=764; Participant characteristics:; - [underlined: Race and/or Ethnicity: NR]; - [underlined: SEP]: All with University education; ∼32–37% with degree; ∼44–49% with Master’s degree; ∼20% with PhD; - [underlined: Selection:] Excluded those with missing baseline or 6-yr cognition data; implausible TICS-m score (n=1); with missing saliva sample or for whom ApoeE alleles could not be determined; with extreme energy intakes | - DP Age(s): 55+ y at baseline; ∼60–61 y (mean); - DP(s) examined: Mediterranean Diet Score (MDS) [Trichopolou 2003]; - DP Components:; - MDS, Positive: Vegetables; Legumes; Fruit, Nuts; Cereals; Fish; MUFA/SFA. Negative: Red and Processed Meat; Dairy Products. Neutral: Alcohol; - DP Method(s): Index/Score; Comparisons: Categorical, high (5–9) vs. low (0–4) | Follow-Up Duration: 6 y; Results:; ΔCognitive function (adjusted difference, 95% CI); Low MDS-no HTN, 0, ref; Low MDS-w/HTN, −0.62, 95% CI: −1.09, −0.15; p-trend=0.010; R2=30%; High MDS-no HTN, 0, ref; High MDS-w/HTN, −0.11, 95% CI: −0.61, 0.38; p-trend=0.660; R2=38%; Significant difference between low adherence-w/ HTN vs. other groups (low adherence-no HTN; high adherence (no & w/ HTN); Summary: Inverse: low MDS & greater Δcognitive function in those with HTN (vs. low MDS-no HTN, high MDS-w/ HTN, high Med-no HTN) | - Did not account for: SEP, Race and/or Ethnicity (Spanish), Physical activity, Smoking; - MDS was treated as stratification variable, not main effect; direct comparison of low vs. high MDS not conducted; - Diet assessment: FFQ assessed once at baseline; - Outcome measurement: TICS-m; assessed at baseline and 6y; Funding: Instituto de Salud Carlos III, European Regional Development Fund
Rodrigues, 2020 ^59^; Portugal; SWITCHBOX consortium; Analytic N=76; Participant characteristics:; - [underlined: Race and/or Ethnicity: NR]; - [underlined: SEP]: Education, mean 5.8 (4.1) y; - Occupation: 18% employed; 74% retired; 8% unemployed; - [underlined: Selection:] Excluded those with or who: had inability/incapacity to understand informed consent or attend visits, choosen to withdraw, with dementia or other neuro-related disorder (via medical records) | - DP Age(s): 66.4 (7.8) y; - DP(s) examined: Mediterranean Diet Adherence Screener (MEDAS) [Schroder 2011]; - DP Components:; - MEDAS, Positive: Vegetables; Pulses; Fruit; Nuts; Fish; White Meat Over Red Meat; Olive Oil; Olive Oil as Principal Cooking Fat; Red Wine; Sofritas (dishes with tomato, garlic, onion, leek, olive oil). Negative: Commercial Pastries; Red Meat or Sausages; Animal fat; Sugar-Sweetened Beverages; - DP Method(s): Index/Score; Comparisons: Categorical, Low MEDAS (<10) vs. High (≥10) REF | Follow-Up Duration: 18 mos. (range: 16 to 25); Results:; MEDAS & Executive functioning, β: 0.232 (95% CI: 0.020, 0.215);p=0.02; MEDAS & Memory scores, β: 0.213 (95% CI: 0.006, 0.247); p=0.06; Summary: Positive: MEDAS & Executive Fx; NS/Positive: MEDAS & Memory | - Did not account for: Race and/or Ethnicity; - Also measured total gray matter volume, total white matter volume, total brain volume; - Diet assessment: 24-h recall once at baseline; - Outcome measurement: Composite scores transformed/scaled from a cognitive battery of tests (MMSE; SRT, multi-trial verbal learning and selective reminding; STROOP); Funding: European Regional Development Fund (FEDER) and the Operational Programme Competitiveness Factors (COMPETE)
Samuelsson, 2022 ^60^; Sweden; Gothenburg H70 Birth Cohort Studies; Analytic N=602; Participant characteristics:; - [underlined: Race and/or Ethnicity]:100% Swedish; - [underlined: SEP]: Education > 6 or 7y: 40%; - [underlined: Selection:] Excluded those who had missing dietary, dementia, or genotype data | - DP Age(s): 70.6y, mean; - DP(s) examined: “Western”; “Healthy”; - DP Components:; - “Healthy”: Positive: fish and seafood; meat and processed meat; eggs; potatoes; vegetables, pulses, nuts, and seeds; fruits and berries; cheese; fiber-rich bread; cereals; sweet bakery; desserts; sweet condiments; margarine; vegetable oil; juice; alcoholic beverages (higher intakes of vitamins C and E, folate, fiber, PUFA); - “Western”: Meat and processed meat; potatoes; higher fat milk products; cream and creme fraiche; cheese; refined bread; sweet bakery; margarine; alcoholic beverages. Negative: vegetables, pulses, nuts, and seeds; fruits and berries; low-fat and non-fat (low-sugar) milk products (and lower intakes of vitamin C, folate, fiber); - DP Method(s): RRR; Comparisons: Continuous, “Healthy” or “Western” DP | Follow-Up Duration: 12.8y, mean; Results:; “Healthy” & incident Dem, HR: 0.83, 95% CI: 0.67, 1.03; p=0.09; “Western” & incident Dem, HR: 1.06, 95% CI: 0.90, 1.25; p=0.48; Summary: NS/Inverse: “Healthy” DP & Dem; NS/Positive: “Western” DP & Dem | - Did not account for: Race and/or Ethnicity (Swedish birth cohort), SEP; - Diet assessment: Diet Hx at baseline; - Outcome measurement: Dem based on Dx at exams via DSM-III (same method 1992 through 2016); Funding: University of Gothenburg
Shang, 2021 ^61^; China; Chinese Longitudinal Healthy Longevity Survey (CLHS); Analytic N=2307; Participant characteristics:; - [underlined: Race and/or Ethnicity: NR] (Chinese); - [underlined: SEP]: Education: 80% with <5y; Rural 55–73%; - [underlined: Selection:] Excluced those: <55y, missing diet/sleep data, cognitive evals, or only had 1 cognitive eval; who had stroke, heart Dz, Cx, or psychiatric condition at baseline | - DP Age(s): 63.3y (SD: 7); 55–89y at baseline; - DP(s) examined: “Dairy-fruits-fast foods”; “Grains-vegetables-pork”; “Plant-based”; “Beans-mushroom”; “Beverages-nuts” DP; - DP Components:; - “Dairy-fruits-fast foods”; Positive: dairy, fruits, fast foods, eggs; - “Grains-vegetables-pork”; Positive: low-fiber grains, vegetables, pork; - “Plant-based”; deep fried grains, higher-fiber grains, fruits, beans. Negative: low-fiber grains, candies, sugar; - “Beans-mushroom”; Positive: beans, edible fungi & algae (mainly mushrooms), snacks; - “Beverages-nuts”; Positive: beverages, nuts, poultry; - DP Method(s): Factor/Cluster; Comparisons: Categorical, quintiles (Q1, OR: 1 ref;) and linear trend for each DP | Follow-Up Duration: 7y median (age 70y); Results:; Dairy-Fruit-Fast foods DP & CD, OR (95% CI); Q2, 1.17 (0.78, 1.77); Q3, 0.90 (0.59, 1.37); Q4, 0.70 (0.45, 1.07); Q5, 0.71 (0.45, 1.12); p-trend=0.0197; Grains-Veg DP & CD, OR (95% CI); Q2, 1.54 (1.01, 2.34); Q3, 1.40 (0.91, 2.17); Q4, 1.21 (0.79, 1.87); Q5, 1.03 (0.66, 1.61); p-trend=0.66; Plant-based & CD, OR (95% CI); Q2, 0.80 (0.53, 1.22); Q3, 0.83 (0.55, 1.23); Q4, 0.61 (0.40, 0.95); Q5, 1.09 (0.73, 1.62); p-trend=0.88; Beans-Mushroom & CD, OR (95% CI); Q2, 1.17 (0.77, 1.76); Q3, 1.02 (0.68, 1.56); Q4, 0.97 (0.57, 1.56); Q5, 0.75 (0.49, 1.16); p-trend=0.0295; Beverages-Nuts & CD, OR (95% CI); Q2, 1.38 (0.91, 2.09); Q3, 1.03 (0.66, 1.59); Q4, 0.83 (0.54, 1.26); Q5, 0.65 (0.42, 1.01); p-trend=0.0050; Results for change in cognitition (β (95% CI)) were similar to above “Beans-Mushroom” DP & MCI, OR: 0.49, 95% CI: 0.30, 0.81; Other DPS, NS (Supplementary Table 9); Summary: NS/Inverse: “Dairy-fruits-fast foods” DP & CD, Δ cognition; NS/Null: “Grains-vegetables-pork” DP & CD, Δ cognition; NS/Null: “Plant-based” DP & CD, Δ cognition; Inverse: “Beans-mushroom” DP & CD, Δ cognition, MCI; Inverse: “Beverages-nuts” DP & CD, Δ cognition | - Did not account for: Race and/or Ethnicity (all Chinese), SEP although adjusted for living area; - Main goal seems to be role of sleep duration (lack of clear reporting for all DP & CD/MCI in results section); - Diet assessment: 24h-recall (3 consecutive days) at each wave; - Outcome measurement: CD odds based on change in global cognitive z-score <1SD below mean; Funding: National Institute for Nutrition and Health, China CDC; Carolina Population Center; UNC-CH; NIH; Fundamental Research Funds of the State Key Laboratory of Ophthalmology
Shannon, 2023 ^62^; United Kingdom; UK Biobank; Analytic N=60298; Participant characteristics:; - [underlined: Race and/or Ethnicity]:100% White (British, Irish, or other white); - [underlined: SEP]: Education: Higher 55.2%; Vocational 10.2%; Uppder secondary 5.6%; Lower secondary 15.4%; Other 13.6%; - SES: 1 (least deprived) 23.8%; 2–4 63.3%; 5 (most deprived) 12.9%; - [underlined: Selection:] Excluded those <60 y at baseline; those self-reporting race other than white; without genetic data; missing dietary or covariate data | - DP Age(s): 63.8 y (mean); ≥60 y at baseline; - DP(s) examined: Mediterranean Diet Adherence Screener (MEDAS) [Estruch, 2013; Papadaki, 2018]; - Pyramid Mediterranean Diet Score (PyrMDS) [Tong 2016]; - DP Components:; - MEDAS: Positive: Vegetables; Fruit; Legumes; Nuts; Fish; White Meat Over Red Meat; Olive Oil; Olive Oil as Principal Cooking Fat; Wine; Sofritas [pasta/vegetable dishes with Tomato Sauce (tomato, garlic, onion, leek, olive oil)]; Negative: Sweets or Pastries; Red Meat or Sausages; Butter, maragarine; Sugar-Sweetened Beverages; - PyrMDS: Positive: Vegetables; Legumes; Fruit; Nuts; Cereals; Fish; White Meat; Eggs; Dairy; Olive Oil. Negative: Potato; Red Meat; Processed Meat; Sweets; Alcohol; - DP Method(s): Index/Score; - Comparisons: Categorical, tertiles; Continuous, per 1 pt | Follow-Up Duration: 9.1 y (mean); Results:; MEDAS; T1, HR: 1, ref; T2, HR: 0.922, 95% CI: 0.788, 1.079, p-trend=0.314; T3, HR: 0.770, HR: 0.650, 0.912, p-trend=0.003; Per 1 pt, HR: 0.931, 95% CI: 0.895, 0.969, p-trend<0.001; PyrMDS; T1, HR: 1, ref; T2, HR: 0.993, 95% CI: 0.849, 1.162, p-trend=0.931; T3, HR: 0.859, 95% CI: 0.726, 1.018, p-trend=0.079; Per 1 pt, HR: 0.958, 95% CI: 0.9222, 0.996, p-trend<0.031; Summary: Inverse: MEDAS & dementia (continuous; T1 vs. T3); Inverse: PyrMDS & dementia (continuous; NS/Null Tertiles) | - Did not account for: Anthropometry; - Diet assessment: Diet assessed once at baseline using ≥1 24-hr recall (sensitivity analyses conduPNcted using ≥2 24-hr recall showed similar results except that PyrMDS by tertiles showed significant inverse relationship for T1 vs. T3); - Outcome measurement: Dementia derived from hospital admission and death records; Funding: UK Nutrition Research Partnership (UK NRP)
Tanaka, 2018 ^63^; Italy; InCHIANTI; Analytic N=832; Participant characteristics:; - [underlined: Race and/or Ethnicity: NR] (Italian); - [underlined: SEP]: Education 5.3y ± 3.3; - [underlined: Selection:] Excluded those with cognitive impairment, <65y; | - DP Age(s): ∼75 y (SD: ∼7); 65+y at baseline; - DP(s) examined: Mediterranean Diet Score (MDS) [Trichopolou 2003]; - DP Components:; - MDS, Positive: Vegetables; Legumes; Fruit, Nuts; Cereals; Fish; MUFA/SFA. Negative: Red and Processed Meat; Dairy Products. Neutral: Alcohol; - DP Method(s): Index/Score; Factor/Cluster; Comparisons: Categorical, Medium (Med.) 4–5, High ≥ 6; Low ≤3, REF; continuous per 1 unit MDS | Follow-Up Duration: 10.1y, mean (every 2–3y up to 18y); Results:; MDS & CD, HR (95% CI); per-1pt, 0.88 (0.80, 0.97); p-trend=0.009; Med., 0.75 (0.53, 1.05); p-trend=0.089; High, 0.59 (0.39, 0.88); p-trend=0.011; MDS & Slope in CD 0.4/y, β (SE); per-1pt, 0.081 (0.018);p<0.001; Med., 0.158 (0.072);p=0.028; High, 0.346 (0.077);p<0.001; Summary: Inverse: MDS & CD, Δ CD | - Did not account for: SEP, Race and/or Ethnicity (all Italian and adjusted for study site); - Age range of cohort is 21 to 102y, these analyses restricted to those 65+y; - Baseline MMSE score higher in those with higher MDS adherence; - Diet assessment: FFQ assessed once at baseline; - Outcome measurement: MMSE: CD defined as ≥ 5-pt MMSE decrease; MCI w/o DEM based on MMSE<23 with ADL due to CFx; Dem defined by MMSE <23; Funding: Italian Ministry of Health; NIH
Tangney, 2014 ^64^; United States; Rush Memory and Aging Project (MAP); Analytic N=826; Participant characteristics:; - [underlined: Race and/or Ethnicity: NR]; - [underlined: SEP]: Education, 14.9y mean; - [underlined: Selection:] Excluded those with dementia at baseline; LFU; invalid FFQ; <2 cognitive evals. Note 74% female | - DP Age(s): 81.5y ± 7.1y; - DP(s) examined: Mediterranean-based Diet Score (MedDietScore) [Panagiotakos 2007]; - adjusted DASH Score (aDASH) [Folsom, 2007]; - DP Components:; - MedDietScore, Positive: Vegetables; Potatoes; Legumes; Fruit; Whole Grains; Fish; Olive Oil. Negative: Red and Processed Meat; Poultry; Full-Fat Dairy; Alcohol; - aDASH, Positive: Vegetables; Nuts and Legumes; Fruit; Grains; Dairy; Negative: Fat; Saturated Fat; Meat, Poultry, Fish; Sweets; Sodium; - DP Method(s): Index/Score; Factor/Cluster; Comparisons: Continuous, per unit DASH, MedDietScore; Categorical, T3 v. T1 (ref) | Follow-Up Duration: 4.1y, mean (range 1–10y); Results:; aDASH &; CD/Global CFx, β (SEE): 0.007(0.003),p=0.03; T3 v. T1, 0.022(0.011),p=0.04; Episodic, β (SEE): 0.008(0.004),p=0.04; T3 v. T1, 0.024(0.013),p=0.07 (T2, NS); Visuospatial, β (SEE): 0.007(0.004),p=0.07; T3 v. T1, 0.018(0.013),p=0.17; Perceptual,β (SEE): 0.007(0.004),p=0.06; T3 v. T1, 0.021(0.012),p=0.08; Semantic, β (SEE): 0.009(0.004),p=0.02; T3 v. T1, 0.023(0.012),p=0.05; Working, β (SEE): 0.005(0.004),p=0.15; T3 v. T1, 0.016(0.012),p=0.2; MedDietScore & CD/Global CFx, β (SEE): 0.002(0.001),p=0.01; T3 v. T1, 0.034(0.012),p=0.003 (T2, NS); Episodic, β (SEE): 0.003(0.001),p=0.02; T3 v. T1, 0.04(0.015),p=0.007; Visuospatial, β (SEE): 0.002(0.001),p=0.08; T3 v. T1, 0.022(0.014),p=0.12; Perceptual, β (SEE): 0.002(0.001),p=0.07; T3 v. T1, 0.024(0.013),p=0.07; Semantic, β (SEE): 0.003(0.001),p=0.02; T3 v. T1, 0.033(0.013),p=0.01; Working, β (SEE): 0.002(0.001),p=0.14; T3 v. T1, 0.033(0.013),p=0.01; Summary: Inverse: aDASH & CD (Positive: DASH & Global CFx; per-unit & Episodic, Semantic; NS: Perceptual; Visuospatial); Inverse: MedDietScore & CD (Positive: MedDietScore & Global CFx; per-unit & Episodic, Semantic, Perceptual Memory; NS: Visuospatial) | - Did not account for: SEP; Race and/or Ethnicity; Physical activity; Smoking; Anthropometry; - Diet assessment: FFQ assessed once at baseline; - Outcome measurement: CD based on composite of average z-scores from battery of 19 CFx tests (episodic memory; semantic memory; working memory; perceptual speed; visuospatial ability); Funding: NIA
Thomas, 2024 ^65^; United States; Framingham Offspring Cohort; Analytic N=1644; Participant characteristics:; - [underlined: Race and/or Ethnicity: NR]; - [underlined: SEP]: Education: 45% college grad; 28% some college; 24% high school; 4% less than high school; - Marital status: 70% cohabitating; - [underlined: Selection:] Excluded those with Dementia at visit 8, younger than 60 y, missing DNA data, Dem status at F/U, or FFQ at visits 5, 7, and/or 8 | - DP Age(s): 69.7 (6.8) y; - DP(s) examined: Mediterranean-Dash Intervention for Neurodegenerative Delay diet (MIND) [Morris, 2015]; - 2010/2005 Dietary Guidelines for American Index [(DAGI) Fogley-Cawley, 2006](DGAI); - Mediterranean Diet Score (MDS) [Trichopolou 2003]; - DP Components:; - MIND: Positive: Green leafy vegetables; Vegetables; Beans; Berries; Nuts; Whole Grains; Seafood; Poultry; Olive oil; Wine. Negative: Red Meat; Cheese; Pastries and sweets; Butter and stick margarine; Fried/fast food; - DGAI, Positive: Dark Green Vegetables; Orange Vegetables; Starchy Vegetables; Other Vegetables; Variety of Vegetables and Fruits; Legumes; Fruit; Total Grains; Whole Grains; Fish and Seafood; Meat and Legumes; Milk and Milk Products; Low-Fat choices; Dietary Fiber. Neutral: Total Fat; SFA; Trans FA; Cholesterol; Sodium. Negative: Added sugar; Alcohol; - MDS, Positive: Vegetables; Legumes; Fruit and Nuts; Cereals; Fish; MUFA/SFA. Negative: Red and Processed Meat; Dairy Products. Neutral: Alcohol; - DP Method(s): Index/Score; Comparisons: Continuous per-1 SD increase | Follow-Up Duration: 6.9y, median (max: 13.6); Results:; Total effect: MIND & Dem, β: −28.9, 95% CI: −52.5, −5.2 (supplementary table 2); Total effect: MDS & Dem, β: −33.3, 95% CI: −54.5, −12.1 (supplementary table 1); Total effect: DGAI & Dem, β: −32.7, 95% CI: −56.0, −9.6 (supplementary table 1); Summary: Inverse: MIND & Dem Inverse: DGAI & Dem; Inverse: MDS & Dem | - Did not account for: SEP (MDS; DGAI; adjusted for marital status in MIND); Race and/or Ethnicity, Physical activity (MDS, DGAI), Anthropometry (MDS, DGA), Education (MDS, DGAI), Smoking (MDS, DGAI); - Effect of DGAI & Dem was mediated ∼15% by DunedinPACE; Additional adjustment for blood cell count did not impact main results; - Diet assessment: FFQ assessed every 4–6y; DP averaged from FFQ at 5th, 7th and 8th visits; - Outcome measurement: cases of Dem, n=140; Dem Dx based on: DSM-IV from committee review after neuro-exam preceded by low MMSE; physical referral; medical record; or subjective report of cognitive impairment; Funding: NIA
Tong, 2021 ^66^; Singapore; Singapore Chinese Health Study (SCHS); Analytic N=14683; Participant characteristics:; - [underlined: Race and/or Ethnicity]:100% Chinese; - [underlined: SEP]: Highest education at baseline:; - No formal, 18%; - Primary school, 44.5%; - Secondary or above, 24.5%; - [underlined: Selection:] Excluded those who did not complete dietary assessments at baseline & f/u; missing cognitive assessment at f/u; those who were mute, blind, or deaf | - DP Age(s): 45–74 y at baseline; - DP(s) examined: DASH Score [Fung 2008] - Modified for this study; - DP Components:; - Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Total Dairy. Negative: Red and Processed Meat; Sweetened Beverages; - DP Method(s): Index/Score; - Comparisons: Categorical, quintiles at basline; Categorical, change group (consistently low, score of −1 to 1; moderate-large decrease, −20 to −4; small decrease, −3 to −2; small increase, 2–3; moderate-large increase, 4–20; consistently high, −1 to 1) | Follow-Up Duration: 19.7 y (mean); age ∼72.7 y, mean at visit 3; Results:; Baseline DASH & cognitive impairment; Q1, OR: 1, ref; Q2, OR: 0.82, 95% CI: 0.70, 0.96; Q3, OR: 0.65, 95% CI: 0.55, 0.76; Q4, OR: 0.67, 95% CI: 0.56, 0.80; Q5, OR: 0.50, 95% CI: 0.42, 0.59; p-trend<0.0001; Δ DASH & cognitive impairment Consistently low, OR: 1; Summary: Inverse: baseline DASH & cognitive impairment; Inverse: Increase DASH & lower cognitive impairment; Null: Decrease DASH & cognitive impairment | - Did not account for: SEP; - Diet assessment: FFQ at baseline, interviewer-administered dietary screener at 3 yr f/u. Modifactions made to index/score by Fung, 2008 based on data available from dietary assessment: total dairy rather than low-fat dairy, sodium excluded; - Outcome measurement: MMSE - Singapore-modified; Funding: National Medical Research Council, Singapore; Saw Swee Hock School of Public Health, National University of Singapore
Trichopoulou, 2015 ^67^; Greece; European Prospective Investigation into Cancer and Nutrition (EPIC) Greece; Analytic N=401; Participant characteristics:; - [underlined: Race and/or Ethnicity: NR]; - [underlined: SEP]: Education:; - 0–5 years, 11.1% (men), 24.9% (women); - 6–11, 53.5% (men), 33.1% (women); - 12, 10.4% (men), 26.8% (women); - ≥13, 25% (men), 15.2% (women); - [underlined: Selection:] Excluded those missing 1 or both cognitive assessments; those lost to f/u (death, moved outside of Attica, not able to contact) | - DP Age(s): 65+ y at baseline (40–50% age 70–74y; 30–46% age 75y+); - DP(s) examined: Mediterranean Diet Score (MDS) [Trichopolou 2003]; - DP Components:; - Positive: Vegetables; Legumes; Fruit, Nuts; Cereals; Fish; MUFA/SFA. Negative: Red and Processed Meat; Dairy Products. Neutral: Alcohol; - DP Method(s): Index/Score; Comparisons: Categorical, low (0–3 pts), moderate (4–5 pts), high (6–9 pts) | Follow-Up Duration: ∼20 y FFQ 1994–1999; first MMSE 2004–2006; second MMSE 2011–2012; Results:; MDS & ΔMMSE −4 to −1 vs ≥0 (mild CD); Low, OR: 1, ref; Moderate, OR: 0.75, 95% CI: 0.41, 1.37, p-trend=0.348; High, OR: 0.46, 95% CI: 0.25, 0.87, p-trend=0.017; p-trend (all 3 categories)=0.012; MDS & ΔMMSE ≤ −5 vs Ȧ0 (substantial CD); Low, OR: 1, ref; Moderate, OR: 0.72, 95% CI: 0.31, 1.65, p-trend=0.441; High, OR: 0.34, 95% CI: 0.13, 0.89, p-trend=0.029; p-trend (all 3 categories)=0.025; Summary: Inverse: MDS & CD (mild, substantial) | - Did not account for: SEP, Race and/or Ethnicity; - Mean age 74 at first cognitive exam. Results similar when examining participants ≥75 years old at first MMSE evaluation; - Diet assessment: FFQ once at baseline; - Outcome measurement: CD determined by MMSE score: mild performance decline defined as change in MMSE −4 to −1 vs ≥0; substantial performance decline defined as change in MMSE ≤ −5 vs ≥0; Funding: Hellenic Health Foundation, the European Union CHANCES project, Stavros Niarchos Foundation
van Soest, 2023 ^68^; The Netherlands; B-Proof trial, Control group only; Analytic N=314; Participant characteristics:; - [underlined: Race and/or Ethnicity]: White 95%: Asian 4%: Other 1%; - [underlined: SEP]: Education: 43% Low; 24% Mid; 34% High; - [underlined: Selection:] Excluded those without complete data (cognitive tests, FFQ); with unreliable TEI; aged <65 y | - DP Age(s): 72.1 (5) y; ≥65y at baseline; - DP(s) examined: adapted Plant-Based Diet Index (PDI), healthful/unhealthful: ahPDI/auPDI [Satija, 2016, modified Kim 2018 (no alcohol or margarine)]; - DP Components:; - aPDI: Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Negative: Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; - ahPDI: Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Negative: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animalbased foods; - auPDI: Negative: Whole grains; Fruits; Vegetables; Nuts; Legumes; Vegetable oils; Tea/coffee; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; Positive: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; - DP Method(s): Index/Score; Comparisons: Continuous per-10pt increase and categorical by tertiles (T1, HR: 1 REF) for PDI, hPDI, uPDI | Follow-Up Duration: 2y; Results:; aPDI & CD; per-10-pt, β: −0.03, 95% CI: −0.08, 0.02; p= 0.30; T2, β: −0.08, 95% CI: −0.16, −0.01; p= 0.03; T3, β: −0.04, 95% CI: −0.11, 0.04; p= 0.35; ahPDI & CD; per-10-pt, β: 0.03, 95% CI: −0.01, 0.08; p=0.17; T2, β: 0.00, 95% CI: −0.07, 0.07; p= 0.92; T3, β: 0.05, 95% CI: −0.03, 0.12; p= 0.21; auPDI & CD; per-10-pt, β: −0.05, 95% CI: −0.09, 0.00; p= 0.04; T2, β: −0.03, 95% CI: −0.10, 0.05; p= 0.47; T3, β: −0.04, 95% CI: −0.11, 0.04; p= 0.33; Additional results mostly NS as reported by outcome domains (episodic memory, information processing; executive Fx) per CD except: hPDI significantly associated with better/improved working memory/attention and auPDI significantly associated with worse (steeper decline) in attention/working memory; Summary: NS/Null: aPDI & CD NS/Null: ahPDI & CD (trend for preserved attention); NS/Null: auPDI & CD (trend for steeper decline in attention) | - Did not account for: SEP; - Participants from a B-vitamin supplementation trial to reduce fracture risk, cognition was secondary interest; - Credit given for Race and/or Ethnicity KC but there is a trending (p=0.06) difference between tertiles of PDI; - Diet assessment: FFQ assessed once at baseline; - Outcome measurement: Composite scores transformed/scaled from a cognitive battery of tests (MMSE; RAVLT; Digit Span; TMT; STROOP; Digit Modality; Letter Fluency); Funding: The Netherlands Organization for Health Research and Development; Hauge; Dutch Dairy Association; Netherlands Consortium for Healthy Ageing; Ministry of Economic Affairs; Wageningen University; VU Medical Center; Erasmus Medical Centre
Vercambre, 2012 ^69^; United States; Women’s Antioxidant Cardiovascular Study (WACS); Analytic N=2504; Participant characteristics:; - [underlined: Race and/or Ethnicity]:94% White; 3% “African-American”; - [underlined: SEP]: All health professionals; Education: 8–15% Advanced degree (MS/PhD); ∼58–64% Married; - [underlined: Selection:] Excluded those with incomplete dietary info, or age younger than 40 for the parent trial and younger than 65 for this analysis; Included only female health professionals with CVD or 3+ risk factors with complete dietary data and cognitive function tests | - DP Age(s): 72–73y, mean (range: 66–91y); - DP(s) examined: Mediterranean Diet Score (MDS) [Trichopolou 2003]; - Mediterranean-based Diet Score (MedDietScore) [Panagiotakos 2007]; - DP Components:; - MDS, Positive: Vegetables; Legumes; Fruit, Nuts; Cereals; Fish; MUFA/SFA. Negative: Red and Processed Meat; Dairy Products. Neutral: Alcohol; - MedDietScore, Positive: Vegetables; Potatoes; Legumes; Fruit; Whole Grains; Fish; Olive Oil. Negative: Red and Processed Meat; Poultry; Full-Fat Dairy; Alcohol (all=“Wine”); - DP Method(s): Index/Score; Comparisons: Catergorical High or Mid vs. Low MDS (0, ref) or continuous, per 1-pt; MedDietScore NR | Follow-Up Duration: 5.4y, mean total (range 4.1–6.1); Results:; mean differences (95% CI); Global CF; Mid-MDS, 0.01 (−0.01, 0.02); High MDS, 0.00 (−0.02, 0.01); p=0.88; per-1 pt MDS, −0.001; p=0.40; MedDietScore, p=0.58 (data NR); TICS-m; Mid-MDS, 0.02 (−0.05, 0.08); High MDS,−0.03 (−0.11, 0.05); p=0.53; MedDietScore, p=0.25 (data NR); Verbal Memory; Mid-MDS, 0.00 (−0.01, 0.02); High MDS, 0.00 (−0.02, 0.02) p=0.97; MedDietScore, p=0.39 (data NR); Category Fluency; Mid-MDS, 0.01 (−0.08, 0.11); High MDS, −0.03 (−0.14, 0.08) p=0.64; MedDietScore, p=0.52 (data NR); Summary: NS/Null: MDS & CD (global CFx, TICS; verbal memory; category fluency); NS/Null: MedDietScore & CD (global CFx, TICS; verbal memory; category fluency) | - Did not account for: None (all); Race and/or Ethnicity (94% White); - Sample comprised predominantly of women with CVD (or 3+ risk factors); - Diet assessment: FFQ assessed once at baseline; - Outcome measurement: TICS-m +Telephone adaptation of MMSE (not mention if validated); Funding: NIH; AHA; Bettencourt-Schueller Foundation
Vlachos, 2022 ^70^; Greece; Hellenic Longitudinal Investigation of Aging and Diet (HELIAD); Analytic N=910; Participant characteristics:; - [underlined: Race and/or Ethnicity: NR] (Greek); - [underlined: SEP]: Education: 8.3 (4.9)y, mean (SD) (range: 0–21y); - [underlined: Selection:] Excluded those with dementia at baseline or no available dietary info or cognitive F/U | - DP Age(s): ∼73y; ≥65y at baseline; - DP(s) examined: Mediterranean-based Diet Score (MedDietScore) [Panagiotakos 2007]; - DP Components:; - MedDietScore, Positive: Vegetables; Potatoes; Legumes; Fruit; Whole Grains; Fish; Olive Oil. Negative: Red and Processed Meat; Poultry; Full-Fat Dairy; Alcohol; - DP Method(s): Index/Score; Comparisons: Continuous, MedDietScore per 10pt | Follow-Up Duration: 3.1 (0.8)y, mean (range: 1.2 to 7.3y); Results:; MDS per 10pt & SCD, β: −0.007; p=0.005 (ie, 7% reduction in CD); Summary: Inverse: MDS & SCD | - Did not account for: SEP, Race and/or Ethnicity (Greek), Smoking; Anthropometry,; - Study had high LFU; - Diet assessment: FFQ assessed once at baseline; - Outcome measurement: SCD as a surrogate for preclinical Dem, defined as a positive response for memory, naming, orientation and calculation decline domains [based on structured list of Jessen et al. 2014]; Funding: Alzheimer’s Association; European Social Fund; Ministry of Health and Social Solidarity
Vu, 2022 ^71^; United States; Chicago Health and Aging Project (CHAP), Rush Memory and Aging Project (MAP), and Women’s Health Initiative Memory Study (WHIMS); Analytic N=8482 (MAP n=725; CHAP n=2449; WHIMS n=5308); Participant characteristics:; - [underlined: Race and/or Ethnicity]: CHAP: 60% Black; 40% White; MAP: NR; WHIMS: included only those of European ancestry (89% of original sample); - [underlined: SEP]: Education:; - University degree, ∼21–40% in WHIMS (n/a in MAP, CHAP); - Total years, ∼11–15 in MAP, CHAP (n/a in WHIMS); - [underlined: Selection:] CHAP: excluded those missing genetic or dietary data; - MAP: Recruited from individual homes. retirement communities, and senior public housing; included those free of dementia at aseline and agreed to annual clincial evaluations/organ donation at death; - WHIMS: excluded those with dementia at basline; only included those of European ancestry with genetic data | - DP Age(s): ≥ 65 y at baseline; mean ∼70–82; - DP(s) examined: Mediterranean-Dash Intervention for Neurodegenerative Delay diet (MIND) [Morris, 2015]; - DP Components:; - MIND, Positive: Green leafy vegetables; Vegetables; Beans; Berries; Nuts; Whole Grains; Seafood; Poultry; Olive oil; Wine. Negative: Red Meat; Cheese; Pastries and sweets; Butter and stick margarine; Fried/fast food; - DP Method(s): Index/Score; - Comparisons: Categorical, tertiles; Continuous, per 1-pt | Follow-Up Duration: NR; Results:; MIND & CD; MAP; T1, β: 1, ref; T2, β: 0.006, 95% CI: −0.01, 0.02, p-trend=0.50; T3, β: 0.03, 95% CI: 0.01, 0.05, p-trend=0.001; Per 1-pt, β: 0.006, 95% CI: 0.003, 0.01, p-trend=0.002; CHAP (White); T1, β: 1, ref; T2, β: 0.0001, 95% CI: −0.01, 0.01, p-trend=0.99; T3, β: −0.0008, 95% CI: −0.01, 0.01, p-trend=0.89; Per 1-pt, β: −0.0004, 95% CI: −0.003, 0.002, p-trend=0.78; CHAP (Black); T1, β: 1, ref; T2, β: 0.0003, 95% CI: −0.01, 0.01, p-trend=0.95; T3, β: −0.003, 95% CI: −0.01, 0.01, p-trend=0.51; Per 1-pt, β: −0.00002, 95% CI: −0.003, 0.003, p-trend=0.99; MIND & All-cause Dem; MAP; T1, HR: 1, ref; T2, HR: 0.85, 95% CI: 0.62, 1.16, p-trend=0.31; T3, HR: 6.65, 95% CI: 0.42, 0.92, p-trend=0.02; Per 1-pt, HR: 0.91, 95% CI: 0.83, 1.00, p-trend=0.06; WHIMS; T1, HR: 1, ref; T2, HR: 0.87, 95% CI: 0.79, 0.97, p-trend=0.008; T3, HR: 0.80, 95% CI: 0.72, 0.89, p-trend<0.0001; Per 1-pt, HR: 0.95, 95% CI: 0.92, 0.97, p-trend<0.0001; CHAPS (White); T1, OR: 1, ref; T2, OR: 0.87, 95% CI: 0.30, 2.54, p-trend=0.80; T3, OR: 1.23, 95% CI: 0.47, 3.18, p-trend=0.68; Per 1-pt, OR: 1.00, 95% CI: 0.81, 1.25, p-trend=0.97; CHAPS (Black); T1, OR: 1, ref; T2, OR: 0.86, 95% CI: 0.36, 2.05, p-trend=0.74; T3, OR: 1.48, 95% CI: 0.51, 4.27, p-trend=0.47; Per 1-pt,, OR: 1.08, 95% CI: 0.79, 1.48, p-trend=0.61; MAP, MIND & Alz, T1, HR: 1, ref; T2, NR; T3, HR: 0.62, 95% CI: 0.42, 0.92; CHAP, MIND & Alz, data NR, p-trend>0.05; Summary: Null: MIND & Dem, CHAP (White, Black); Inverse: MIND & Dem, MAP & WHIMS; Null: MIND & CD CHAP; Inverse: MIND & CD, MAP; Null: MIND & Alz, CHAP; Inverse: MIND & Alz, MAP | - Did not account for: Race and/or Ethnicity (MAP only); - Exposure, outcome, and covariate assessments different between cohorts; - Diet assessment: FFQ assessed once for this analysis in each cohort; - Outcome measurement: WHIMS: modified MMSE prior to 2008; TICS-m after 2008; - MAP & CHAP: clinical evaluations in random sample for dementia and Alzheimer’s Dz; Dx based on NIH (NINCD) and Alzheimer’s Dz and Related Disorders Assoc; Funding: NIH (NIA)
Wade, 2019 ^72^; United States; Maine-Syracuse Longitudinal Study (MSLS); Analytic N=530; (≥70y, n=139; <70y, n=391); Participant characteristics:; - [underlined: Race and/or Ethnicity]: Non-African-American, 94%; African-American, 6%; - [underlined: SEP]: Education, 14.7y mean; - [underlined: Selection:] Excluded those with or who had: missing data; stroke, Dem, renal dialysis; inability to read English; prior alcohol abuse; moved > 100 mi | - DP Age(s): 61.6y ± 11.8y; - DP(s) examined: literature Mediterranean Diet Score (LitMDS) [Sofi 2014]; - DP Components:; - LitMDS, Positive: Vegetables; Legumes; Fruit and Nuts; Cereals; Fish; Olive Oil. Negative: Meat; Dairy Products. Neutral: Alcohol; - DP Method(s): Index/Score; Comparisons: Continuous, per SD LitMDS | Follow-Up Duration: ∼5y; Results:; Age ≥70y, linear models, perSD; LitMDS & ΔSD CFx, unstandardized β (95% CI), p-trend, standardized β global CFx, 0.26 (0.07, 0.45); p=0.01; Std. β 0.71; Visual Spatial memory, 0.28 (0.04, 0.53); p=0.02; Std. β 0.72; Verbal memory, 0.18 (−0.13, 0.49); p=0.26; Std. β 0.42; Working memory, 0.25 (−0.03, 0.53); p=0.08; Std. β 0.67; Scanning tracking, 0.23 (0.03, 0.44); p=0.02; Std. β 0.62; Abstract reasoning, 0.03 (−0.33, 0.39); p=0.88; Std. β 0.07; Similar results reported for quadratic models; Age <70y, linear models, perSD; LitMDS & ΔSD CFx, unstandardized β (95% CI), p-trend, standardized β global CFx, 0.01 (−0.06, 0.09); p=0.72; Std. β 0.04; Visual Spatial memory, −0.01 (−0.10, 0.10); p=0.97; Std. β −0.01; Verbal memory, −0.01 (−0.14, 0.12); p=0.87; Std. β −0.03; Working memory, 0.03 (−0.10, 0.15); p=0.66; Std. β 0.07; Scanning tracking, −0.02 (−0.11, −0.07); p=0.67; Std. β −0.06; Abstract reasoning, 0.05 (−0.09, 0.18); p=0.50; Std. β 0.14; Similar results reported for quadratic models; Summary: Inverse: LitMDS in age ≥70y & CD (Positive: LitMDS & CFx, Visual Spatial Org. & Memory; Scanning & Tracking);; NS/Null: LitMDS in age < 70y & CD; CFx | - Did not account for: SEP; Anthropometry; - Diet assessment: Nutrition and Health Questionnaire once at Wave 6; - Outcome measurement: CD based on composite of z-scores from battery of CFx tests (Visual Spatial Organisation and Memory, Verbal Episodic Memory, Scanning and Tracking, Working Memory and Abstract Reasoning); Funding: NIH (NHLBI; NIA)
Wagner, 2020 ^2^; United States; NHS; Analytic N=14956; Participant characteristics:; - [underlined: Race and/or Ethnicity: NR]; - (other NHS studies primarily (>90%) white); - [underlined: SEP]: Educational level:; - RN, ∼77=78%; - Bachelor’s degree, ∼16–17%; - Master’s or doctoral degree, ∼6%; - [underlined: Selection:] Excluded those w cognitive impairment at first cognitive interview; those without f/u measure of cognitive function; those without at least one measure of lifestyle factor during f/u | - DP Age(s): 61 y, mean; - DP(s) examined: Alternate Med Diet Score (aMED) [Fung 2005]; - DP Components:; - Positive: Vegetables (not potatoes); Legumes; Fruit; Nuts; Whole Grains; Fish; MUFA/SFA. Negative: Red and Processed Meat. Neutral: Alcohol; - DP Method(s): Index/Score; Comparisons: Continuous, mean difference | Follow-Up Duration: 5.7 y (mean); Results:; Case vs. control; 11y, mean difference: −0.18 points, 95% CI: −0.27, −0.09; 7y, mean difference: −0.19 points, 95% CI: −0.28, −0.10; 3y, mean difference: −0.19 points, 95% CI: −0.28, −0.11; Summary: Inverse: Lower aMED for those with vs. without CD (cases vs. controls) | - Did not account for: SEP, Anthropometry, Physical activity, Race and/or Ethnicity, Smoking; - Also examined differences by case vs. control in BMI, physical activity (primary aim of study was not just focused on DPs); - Diet assessment: FFQ every ∼4 y; - Outcome measurement: CD cases defined as those with 10% worst cognitive slopes, controls defined as those with cognitive slope above the median based on TICS; Funding: NIH, France Alzheimer DATALINk, Académie Française, University of Bordeaux
Wagner, 2023 ^73^; United States; Rush Memory and Aging Project (MAP); Analytic N=569; Participant characteristics:; - [underlined: Race and/or Ethnicity]:98% Non-Hispanic White (NHW); - [underlined: SEP]: Education, ∼15 y (mean); - [underlined: Selection:] Excluded those without valid dietary data, cognitive testing; those with mild cognitive impairment at baseline in sensitivity analyses | - DP Age(s): 84.1y (5.8); - DP(s) examined: Mediterranean-Dash Intervention for Neurodegenerative Delay diet (MIND) [Morris, 2015]; - DP Components:; - MIND, Positive: Green leafy vegetables; Vegetables; Beans; Berries; Nuts; Whole Grains; Seafood; Poultry; Olive oil; Wine. Negative: Red Meat; Cheese; Pastries and sweets; Butter and stick margarine; Fried/fast food; - DP Method(s): Index/Score; Comparisons: Categorical, tertiles (T1 ref, mean diff.) | Follow-Up Duration: 9y, mean (range: 1 to 23y); Results:; MIND & CR-slope, mean diff (95% CI); T2, 0.20 (0.01, 0.39); p=0.04; T3, 0.27 (0.05, 0.48); p=0.01; perSD, 0.05 (−0.003, 0.10); p-trend = 0.06; Summary: Positive: MIND & CR | - Did not account for: SEP, Physical activity, Anthropometry; - Diet assessment: FFQ assessed at each annual visit but baseline only used after testing change (very small); - Outcome measurement: CR-slope calculated from global cognition (17 tests from annual cognitive evals) and 9 measures of post mortem neuropathology and reflects estimated residual slope of cognitive change [during F/U]; Funding:
Wang, 2021 ^74^; China; Chinese Longitudinal Healthy Longevity Survey (CLHS); Analytic N=5716; Participant characteristics:; - [underlined: Race and/or Ethnicity: NR] (100% Chinese); - [underlined: SEP]: Estimated across DP quantiles:; - Income: 16–30% poor, 55–59% low, 8–30% middle+;; - Education: ∼2–4y of schooling;; - Marital status: 47–59% widowed; 37–51% living with spouse; - Rural: ∼41–61%; - [underlined: Selection:] Excluded those with missing data (MMSE, diet, or life habit scorse) | - DP Age(s): 82 y (mean); 47 to 114 y at baseline; - DP(s) examined: DP score [Wang, 2021]; - DP Components:; - DP, Positive: Vegetables (fresh), Fruit (fresh); ; Nuts; Staple food (corn, rice, wheat); Fish; Milk. Negative: Meat; Sugar; - DP Method(s): Index/Score; Comparisons: Categorical, quartiles (Q1, HR: 1 ref); continuous | Follow-Up Duration: ∼3–6y; Results:; DP & Odds of MMSE <24, Q1, OR: 1 ref; Q2, OR: 0.95, 95% CI: 0.77, 1.18; Q3, OR: 0.71, 95% CI: 0.56, 0.90; Q4, OR: 0.65, 95% CI: 0.51, 0.81; P<0.001 (p-intx: 0.018); β: 0.43, SE: 0.10; 95% CI: 0.24, 0.63;p<0.001; Stratifications by sex yielded similar results; Summary: Inverse: DP & odds of impaired cognitive function | - Did not account for: Alcohol; TEI; - Alcohol not controlled for in dietary pattern analyses but did not have main effect on cognitive function status when examined separately; - Diet assessment: FFQ assessed once at baseline; - Outcome measurement: MMSE (Chinese version); “Impaired” Cog F(x) based on MMSE <24; Funding: National Key Research and Development Project; Peking University Startup Grant; Beijing Technology and Business University Grant; China-Canada Joint Lab of Food Nutrition and Health
Wu, 2023 ^75^; UK; UK Biobank; Analytic N=180532; Participant characteristics:; - [underlined: Race and/or Ethnicity]: White: 94.8 % – 96.8%; - [underlined: SEP]: Townsend deprivation index: −2.08 ∼ −2.41; - Education level: 40.8 – 45.0% college or higher; - Living alone: 15.8 –19.1%; - [underlined: Selection:] Excluded those with incomplete information on covariates, implausible energy intake, a history of cardiovascular disease, cancer, and dementia or depression at baseline | - DP Age(s): ∼56y (mean); 39–72 y; - DP(s) examined: Plant-Based Diet Index (PDI) [Satija, 2016]; - Healthful PDI (hPDI) [Satija, 2016]; - unhealthful PDI (uPDI) [Satija, 2016]; - DP Components:; - PDI: Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Negative: Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; - hPDI: Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Negative: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; - uPDI: Negative: Whole grains; Fruits; Vegetables; Nuts; Legumes; Vegetable oils; Tea/coffee; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; Positive: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; - DP Method(s): Index/Score; - Comparisons: Categorical: Quintiles; Continuous: per 10-point increase | Follow-Up Duration: 10 y (median); Results:; PDI Q1: HR 1, ref; Q2: HR 0.94, 95% CI: 0.79, 1.12; Q3: HR 0.98, 95% CI: 0.83, 1.17; Q4: HR 0.89, 95% CI: 0.74, 1.06; Q5: HR 1.03, 95% CI: 0.87, 1.23; P for trend=0.99; Per 10-point increase: HR 0.99, 95% CI: 0.90, 1.11; hPDI Q1: HR 1, ref; Q2: HR 0.98, 95% CI: 0.83, 1.17; Q3: HR 0.88, 95% CI: 0.73, 1.05; Q4: HR 0.80, 95% CI: 0.67, 0.96; Q5: HR 0.82, 95% CI: 0.68, 0.98; P for trend<0.01; Per 10-point increase: HR 0.87, 95% CI: 0.79, 0.96; uPDI Q1: HR 1, ref; Q2: HR 0.96, 95% CI: 0.81, 1.16; Q3: HR 1.05, 95% CI: 0.89, 1.23; Q4: HR 1.21, 95% CI: 1.02, 1.45; Q5: HR 1.29, 95% CI: 1.08, 1.53; P for trend < 0.001; Per 10-point increase: HR 1.18, 95% CI: 1.07, 1.29; Summary: Inverse: hPDI & Dementia Positive: uPDI & dementia; Null: PDI & Dementia | - Did not account for: None (all); - There is no interaction between hPDI, uPDI and strata defined by age, sex, BMI, PA, smoking status, HTN and DM.; - Excluding dementia in the first 3 years of follow-up did not change the results.; - Might miss milder dementia cases due to only hospital inpatien; - Diet assessment: web-based self-administered 24-h dietary assessment questionnaire; only the earliest intake data was used; - Outcome measurement: Hospital inpatient data on admissions and diagnoses; Funding: the Study of Diet and Nutrition Assessment and Intervention Technology; Study on Intervention Strategies of Main Nutrition Problems in China; National Natural Science Foundation of China, Tianjin Major Public Health Science and Technology Project, National Health Commission of China, Food Science and Technology Foundation of Chinese Institute of Food Science and Technolocy, 2014 and 2016 Chinese Nutrition Society Nutrition Research Foundation - DSM Research Fund
Yuan, 2022 ^76^; United States; NHS; Analytic N=49493; Participant characteristics:; - [underlined: Race and/or Ethnicity]:97.9% White; - [underlined: SEP]: Education level (1992); - RN: 63.4%; - College degree: 20.2%; - Graduate degree: 10.4%; - Missing: 6.0%; - Partner’s education level (1992); - High school or below: 34.6%; - College: 24.1%; - Graduate degree: 21.0%; - Missing: 20.3%; - [underlined: Selection:] Excluded those with extreme energy intake; without SCD assessment in 2012 or 2014; with Parkinson Dz before 2012 | - DP Age(s): 30–55y at baseline; mean age 48y; - DP(s) examined: alternative Mediterranean Diet Score (aMed) [Fung, 2018 modified Trichopolou, 2003]; - DASH Score [Fung 2008]; - Alternative HEI (AHEI)-2010 [Chiuve 2012]; - DP Components:; - aMED: Positive: Vegetables (not potatoes); Legumes; Fruit; Nuts; Whole Grains; Fish; MUFA/SFA; Neutral: Red and Processed Meat; Neutral: Alcohol; - DASH: Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy. Negative: Red and Processed Meat; Sweetened Beverages; Sodium; - AHEI-2010: Positive: Vegetables (not potatoes, French fries); Fruit; Legumes and Nuts; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA. Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Trans FA; Sodium. Neutral: Alcohol; - DP Method(s): Index/Score; Comparisons: Categorical, quintiles | Follow-Up Duration: 28y, ∼ total; Results:; Moderate Subjective CD; aMED; Q1, OR: 1, ref; Q2, OR: 0.97, 95% CI: 0.92, 1.04; Q3, OR: 0.94, 95% CI: 0.89, 1.01; Q4, OR: 0.93, 95% CI: 0.87, 1.00; Q5, OR: 0.81, 95% CI: 0.75, 0.87; p-trend<0.001; DASH; Q1, OR: 1, ref; Q2, OR: 1.00, 95% CI: 0.94, 1.06; Q3, OR: 0.91, 95% CI: 0.86, 0.97; Q4, OR: 0.92, 95% CI: 0.86, 0.98; Q5, OR: 0.76, 95% CI: 0.71, 0.82; p-trend<0.001; AHEI-2010; Q1, OR: 1, ref; Q2, OR: 0.97, 95% CI: 0.92, 1.04; Q3, OR: 0.99, 95% CI: 0.93, 1.06; Q4, OR: 0.93, 95% CI: 0.87, 0.99; Q5, OR: 0.93, 95% CI: 0.87, 0.99; p-trend=0.015; Severe Subjective CD; aMED; Q1, OR: 1, ref; Q2, OR: 0.87, 95% CI: 0.79, 0.96; Q3, OR: 0.82, 95% CI: 0.74, 0.90; Q4, OR: 0.74, 95% CI: 0.67, 0.83; Q5, OR: 0.57, 95% CI: 0.51, 0.64; p-trend<0.001; DASH; Q1, OR: 1, ref; Q2, OR: 0.93, 95% CI: 0.84, 1.02; Q3, OR: 0.76, 95% CI: 0.68, 0.84; Q4, OR: 0.77, 95% CI: 0.69, 0.85; Q5, OR: 0.61, 95% CI: 0.55, 0.68; p-trend<0.001; AHEI-2010; Q1, OR: 1, ref; Q2, OR: 0.88, 95% CI: 0.80, 0.96; Q3, OR: 0.90, 95% CI: 0.82, 0.99; Q4, OR: 0.84, 95% CI: 0.76, 0.93; Q5, OR: 0.81, 95% CI: 0.73, 0.90; p-trend<0.001; Summary: Inverse: aMED, DASH, and AHEI-2010 & moderate or severe CD (subjective) | - Did not account for: None (all); - Study enrolled 100% female, mostly white (may not translate to other populations) participants; results were similar when adjusted for living arrangement & marital status and when excluding those missing diet scores at each assessment in sensitivity analyses; - Diet assessment: FFQ collected every 4 years; - Outcome measurement: Subjective CD based on seven questions across four domains (memory, executive function, attention, visuospacial skills). Higher score=greater decline. Moderate decline=0.5–2.5 points; severe=3–7 points; Funding: NIH, Zhejiang University Education Foundation Global Partnership Fund, VoLo Foundation
Zhang, 2021 ^81^; China; Effects and Mechanism Investigation of Cholesterol and Oxysterol on Alzheimer’s disease (EMCOA) study; Analytic N=2239; Participant characteristics:; - [underlined: Race and/or Ethnicity]: NR (Chinese); - [underlined: SEP]: Education:; - ≤6 y, 16.0%; - 7–9y, 37.6%; - >9y, 46.4%; - [underlined: Selection:] Excluded those w/ severe disease (e.g., Hxof heart or respiratory failure, renal failure, liver failure, cancer); with neuropsychiatric disorders (e.g., depression and schizophrenia); with conditions known to affect cognitive function (e.g., malignant tumors, a history of traumatic brain injury); long-term frequent intake of drugs and medications; those taking dietary supplements to improve cognitive function | - DP Age(s): 58.8 (4.7) y, mean (50–70 y) at baseline; - DP(s) examined: Chinese Dietary Guidelines Index 2018 (CDGI-2018) [Wang, 2019]; - DP Components:; - CDGI-2018: Positive: Cereals & tubers; Fruit; Vegetables (total, dark); Soybean and nuts; dairy products. Negative: oil; salt; wine. Moderate: meat & poultry; eggs; “aquatic” products; - DP Method(s): Index/Score; Comparisons: Categorical, quartiles | Follow-Up Duration: 2.3 y (median); Results:; MCI (MoCA); Q1, RR: 1, ref; Q2, RR: 0.84, 95% CI: 0.66, 1.07; Q3, RR: 0.68, 95% CI: 0.53, 0.87; Q4, RR: 0.75, 95% CI: 0.58, 0.98; p-trend=0.006; Summary: Inverse: CDGI-2018 & MCI | - Did not account for: SEP, Race and/or Ethnicity; - Diet assessment: FFQ once at baseline; - Outcome measurement: MoCA (Montreal Cognitive Assessment; 30 point maximum). MCI diagnosed if score= 13/14 for illiterate individuals, 19/20 for those with 1 to 6 years of education, and 24/25 for those with 7 or more years of education. Those suspected of having MCI based on their MoCA scores were secondarily examined by neurologists for final diagnosis; Funding: State Key Program of the National Natural Science Foundation of China; National Natural Science Foundation of China
Zhang, 2023 ^78^; Singapore; Singapore Chinese Health Study; Analytic N=16736; Participant characteristics:; - [underlined: Race and/or Ethnicity]:100% Chinese; - [underlined: SEP]: Education: 19% none; 45% primary, 37% high school or above;; - 89% Married; - [underlined: Selection:] Excluded those with or who had missing/incomplete diet/cognitive data | - DP Age(s): 53.5 (6.2) y, mean; - DP(s) examined: Planetary Health Diet (PHD) [Zhang, 2023 adapted from EAT-Lancet and DHD-15 scores]; - DP Components:; - PHD, Positive: Vegetables; Legumes; Fruit; Nuts; Whole Grains; Fish; Unsaturated Fatty acids. Negative: Saturated Fats; Meat (beef, lamb, pork); Added sugar; Grains (All, Refined). Neutral: Eggs; Poultry; Whole milk (or derivatives); Potatoes; - DP Method(s): Index/Score; Comparisons: Continuous per-1 SD increase and by quintiles, Q1, OR: 1 REF | Follow-Up Duration: 20 y, median (age 73.1 (6.4) y mean); Results:; PHD & odds of CD; Q2, OR: 0.91 (0.79, 1.05); Q3, OR: 0.94 (0.81, 1.08); Q4, OR: 0.80 (0.70, 0.93); Q5, OR: 0.72 (0.62, 0.83); p<0.001; per SD, OR: 0.89 (0.85, 0.93); Summary: Inverse: PHD & CD | - Did not account for: None (all); - Results stratified by ApoE e4 status showed stronger association between PHD & CD in non-carriers, not among those at higher genetic risk.; - Diet assessment: FFQ assessed once at baseline; - Outcome measurement: CD based on poor CFx via MMSE using education=specific cutoffs of <18, <21, or <25 if no/primary/secondary education levels (cases, n=2397, 14%); Funding: The National Key Research and Development Program of China; The National Natural Science Foundation of China; The National Medical Research Council, Singapore; The Singapore National Medical Research Council
Zhang, 2023 ^80^; China; The China Health and Nutrition Survey; Analytic N=6308; Participant characteristics:; - [underlined: Race and/or Ethnicity]: Chinese; - [underlined: SEP]: Family Income: Low, 18–27%; Med. 29–33%; High 35–49%; Majority unemployed (∼63–65%) with low/elementary education (∼48–67%); - [underlined: Selection:] Excluded those with abnormal or incomplete data (Diet, BMI, TEI); aged <55 y | - DP Age(s): ≥55y at baseline; - DP(s) examined: “Vegetable-pork”; - DP Components:; - “Vegetable-pork”: high intakes of legume products, vegetables, fruits, nuts, pork, fish, and plant oil; - DP Method(s): RRR; Comparisons: Categorical by quintiles (Q1, OR: 1 REF) for “Vegetable-Pork” DP score | Follow-Up Duration: 21y; Results:; “Vegetable-pork” DP & odds of (poor) global CFx, (95% CI); Q2, OR: 0.82 (0.73, 0.93); Q3, OR: 0.79 (0.69, 0.91); Q4, OR: 0.74 (0.63, 0.86); Regression coefficients (p value); Global Cognitive Score; Q2, β: 0.27 (p=0.030); Q3, β: 0.45 (p<0.001); Q4, β: 0.5 (p<0.001); Verbal memory score; Q2, β: 0.11 (p=0.291); Q3, β: 0.13 (p=0.228); Q4, β: 0.12 (p=0.336); Global Cognitive z-score; Q2, β: 0.05 (p=0.002); Q3, β: 0.08 (p<0.001); Q4, β: 0.09 (p<0.001); Verbal memory z-score; Q2, β: 0.04 (p=0.288); Q3, β: 0.05 (p=0.230); Q4, β: 0.05 (p=0.340); Summary: Inverse: “Vegetable-Pork” DP & CD (odds of poor CFx); Positive: CFx; NS: Verbal memory | - Did not account for: None (all); - Diet assessment: 24-h recall once at baseline; - Outcome measurement: CD defined as TICS-m score of < 9; Funding: Abbott Research Fund for Food Nutrition and Safety from Chinese Institute of Food Science and Technology; NIH, NICHD, NIA, NIDDK
Zhang, 2023 ^77^; United Kingdom; BIOBANK; Analytic N=114684; Participant characteristics:; - [underlined: Race and/or Ethnicity]:100% White; - [underlined: SEP]: SEP: −1.73 (2.78), mean (SD) Townsend; Education: 47% high, 33% intermediate, 20% low;; - [underlined: Selection:] Excluded those self-reporting as non-white (Mixed, South Asian, Black, Chinese, and Others); with Dem at baseline; implausible TEI; missing covariates; without APOE genotype | - DP Age(s): 56.8y, mean (40 to 69y at baseline); - DP(s) examined: healthful Plant-based diet index (hPDI) [Satija, 2016; cited Heianza, 2021]; - Mediterranean Diet Score (MDS) [Trichopolou 2003; cited 2005]; - adapted RFS (aRFS) [Zhang adapted Kant, 2004]; - Mediterranean-Dash Intervention for Neurodegenerative Delay diet (MIND); - DP Components:; - hPDI: Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Negative: Fruit juices; Refined grains; Potatoes; Sugar-sweetened beverages; Sweets/desserts; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; - MDS: Positive: Vegetables; Legumes; Fruit, Nuts; Cereals; Fish/seafood; MUFA/SFA. Negative: Red and Processed Meat; Dairy Products. Neutral: Alcohol; - aRFS: Positive: Vegetables: 1) Tomatoes; 2) Green (Broccoli; Spinach; Mustard, Turnip, Collard Greens); 3) Carrots or Root Vegetables: Green Salad; Sweet Potatoes; Baked or Boiled Potatoes; 4) Other Veg.; Legumes; Fruits (Pome: Apples or Applesauce; Citrus: Oranges; Grapefruits; Cantaloupe; Orange or Grapefruit Juice; Grapefruit; Tropical (Banana, Mango, Pineapple); Stone (Cherry, Prune); Other Fruit Juices; Whole grains (cooked cereals such as oatmeal); High-Fiber Cereals, Dark Breads (whole wheat, rye, pumpernickel), Corn Tortillas and Breads; Lean Meats/Poultry [adaptions removed fish, dairy, and fat]; - MIND (w/o EVOO): Positive: Green leafy vegetables; Vegetables; Beans; Berries; Nuts; Whole Grains; Seafood; Poultry; Wine. Negative: Red Meat; Cheese; Pastries and sweets; Butter and stick margarine; Fried/fast food; - DP Method(s): Index/Score; Comparisons: Categorical, hPDI, MDS, aRFS, MIND tertiles (T1, HR: 1 ref) | Follow-Up Duration: 9.4y; Results:; Each DP & Dem, HR(95% CI); hPDI; T2, 1.02(0.81, 1.27); p=0.888; T3, 0.97(0.77, 1.22); p=0.788; MDS; T2, 0.99(0.81, 1.22); p=0.937; T3, 0.94(0.74, 1.19); p=0.609; aRFS; T2, 0.94(0.74, 1.18); p=0.577; T3, 0.99(0.79, 1.25); p=0.948; MIND; T2, 0.91(0.73, 1.14); p=0.432; T3, 0.89(0.71, 1.12); p=0.32; Main results retained after most sensitivity analysis: Stratification by sex yielded stronger inverse association between MDS, RFS, MIND & Dem among females; Summary: NS/Inverse: hPDI & Dem; NS/Inverse: MDS & Dem; NS/Inverse: aRFS & Dem; NS/Inverse: MIND & Dem | - Did not account for: None (all); - Also reported data on DP & brain volume from MRI in subset; - Diet assessment: 24h-recall, web-based; at least 2x from 5 rounds 2009–2012; - Outcome measurement: Dem based on hospital records and death registry data; Funding: National Natural Science Foundation of China, the Fundamental Research Funds for the Central Universities, the Key Laboratory of Intelligent Preventive Medicine of Zhejiang Province, and the Zhejiang University Global Partnership Fund
Zhang, 2023 ^79^; Japan; National Institute for Longevity Sciences-Longitudinal Study of Aging (NILS-LSA) project; Analytic N=1504; Participant characteristics:; - [underlined: Race and/or Ethnicity]:100% Japanese; - [underlined: SEP]: Education ≥ 13y, 38–54%; ≤ 9y ∼28–44%; - Married: ∼78–84%; - [underlined: Selection:] Excluded those with or who had missing dietary data, missing Dem status or self-reported Dem, MMSE <24, missing covariates, incident Dem in first 5y of F/U | - DP Age(s): ∼71 (mean); 65 to 82y at baseline; - DP(s) examined: weighted Japanese Diet Index, 9-item (wJDI9) [Zhang, 2019]; - Japanese Diet Index, 8-items (JDI8) [Lu, 2021]; - Japanese Diet Index (JDI) [Tomato, 2016; Zhang, 2019]; - Japanese Diet Index, 12 item (mJDI12) [Zhang, 2019]; - DP Components:; - wJ19, Positive: Vegetables (green and yellow); Mushrooms; Seaweeds; Fruit; Soybeans and soy foods; Fish and shellfish; Green tea. Negative: Beef and pork. Neutral/Moderate: Rice; - JDI, Positive: Vegetables (green and yellow); Pickles; Seaweeds; Miso soup; Rice; Fish and shellfish; Green tea. Negative: Beef and pork; Coffee; - JDI8, Positive: Vegetables (green and yellow); Pickles; Seaweeds; Miso soup; Rice; Fish and shellfish; Green tea. Negative: Beef and pork; - mJDI12, Positive: Vegetables (green and yellow); Pickles; Mushrooms; Seaweeds; Miso soup; Fruit; Soybeans and soy foods; Rice; Fish and shellfish; Green tea. Negative: Beef and pork; Coffee; - DP Method(s): Index/Score; Comparisons: Continuous and categorical, JDI tertiles, T1, HR: 1 REF or 11th PD 0 as REF | Follow-Up Duration: 11.4y, median (7.8–15.1 range); Results:; wJDI9 per SD, HR: 0.95, 95% CI: 0.90, 0.995; p=0.033; 11th PDs(mos): 3.9, 95% CI: 0.3, 7.6; p=0.035; T2, HR: 0.97, 95% CI: 0.72, 1.31; p=0.848; 11th PDs(mos): 7.9, 95% CI: −7.6, 23.4; p=0.316; T3, HR: 0.58, 95% CI: 0.40, 0.86; p=0.006; 11th PDs(mos): 36.7, 95% CI: 9.9, 63.4; p=0.007; JDI8 per SD, HR: 1.01, 95% CI: 0.92, 1.10; p=0.919; T2, HR: 1.45, 95% CI: 1.01, 2.09; p=0.044; T3, HR: 1.07, 95% CI: 0.78, 1.47; p=0.688; JDI per SD, HR: 1.00, 95% CI: 0.92, 1.09; p=0.975; T2, HR: 1.27, 95% CI: 0.90, 1.78; p=0.178; T3, HR: 1.20, 95% CI: 0.83, 1.74; p=0.339; JDI12 per SD, HR: 0.96, 95% CI: 0.90, 1.03; p=0.287; T2, HR: 1.04, 95% CI: 0.71, 1.52; p=0.838; T3, HR: 0.88, 95% CI: 0.59, 1.30; p=0.521; Summary: Inverse: wJDI9 & Dem (cont. or T3 v. T1; NS, T2); NS/Null: JDI8 & Dem; NS/Null: JDI & Dem; NS/Null: mJDI12 & Dem | - Did not account for: SEP (marital status); Race and/or Ethnicity (Japanese); - Results for wJD19 & Dem similar when excluding a) participants Dx with Dem within first 10 yrs of f/u, b) only participants w MMSE score ≥28 at baseline; - Diet assessment: 3-d diet record - baseline only; - Outcome measurement: Dem based on Long-term Care Insurance System certifcate; n=225 cases; (excluded Dem cases in first 5y of F/U); Funding: Food Science Institute Foundation, Research Funding for Longevity Sciences from the National Center for Geriatrics and Gerontology, Japan; Grant-in-Aid for Early-Career Scientists of JSPS KAK-ENHI
Zhou, 2021 ^82^; Singapore; Singapore Chinese Health Study; Analytic N=14159; Participant characteristics:; - [underlined: Race and/or Ethnicity]:100% Chinese: 48% Cantonese; 52% Hokkien dialect; - [underlined: SEP]: Education: 20% none, 46% primary; 35% secondary+; - Married 89%; - [underlined: Selection:] Excluded those with or who had: Cx, CVD, DM at baseline, extreme TEI, missing outcome data, younger than 65y. | - DP Age(s): 53.3y, mean (45 to 74y at baseline); - DP(s) examined: Alternate Med Diet Score (aMED) [Fung 2005]; - DASH Score [Fung 2008]; - Alternative HEI (AHEI)-2010 [Chiuve 2012]; - Plant-based diet index (PDI; healthful PDI, hPDI) [Satija, 2016]; - DP Components:; - aMED, Positive: Vegetables (not potatoes); Legumes; Fruit; Nuts; Whole Grains; Fish; MUFA/SFA. Negative: Red and Processed Meat. Neutral: Alcohol; - DASH, Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy. Negative: Red and Processed Meat; Sweetened Beverages; Sodium; - AHEI-2010, Positive: Vegetables (not potatoes); Fruit; Legumes and Nuts; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA. Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Trans FA; Sodium. Neutral: Alcohol; - PDI, Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Negative: Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; - hPDI, Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Negative: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; - DP Method(s): Index/Score; Comparisons: Continuous per-SD and categorical for each DP in quartiles, Q1, OR: 1 REF | Follow-Up Duration: 20y (mean age 73.7y); Results:; each DP & odds of not having CD; aMED; Q2, OR: 1.23 (1.07, 1.41); Q3, OR: 1.44 (1.23, 1.70); Q4, OR: 1.62 (1.37, 1.92); p-trend<0.001; perSD, OR: 1.18 (1.12, 1.25); DASH; Q2, OR: 1.18 (1.03, 1.36); Q3, OR: 1.39 (1.21, 1.61); Q4, OR: 1.46 (1.27, 1.69); p-trend<0.001; perSD, OR: 1.14 (1.09, 1.21); AHEI-2010; Q2, OR: 1.13 (0.99, 1.30); Q3, OR: 1.24 (1.08, 1.43); Q4, OR: 1.36 (1.18, 1.57); p-trend<0.001; perSD, OR: 1.13 (1.08, 1.19); PDI; Q2, OR: 1.13 (0.99, 1.30); Q3, OR: 1.33 (1.15, 1.53); Q4, OR: 1.15 (0.99, 1.33); p-trend=0.02; per SD, OR: 1.06 (1.00, 1.12); hPDI; Q2, OR: 1.11 (0.96, 1.27); Q3, OR: 1.16 (1.01, 1.34); Q4, OR: 1.23 (1.06, 1.43); p-trend=0.007; per SD, OR: 1.07 (1.02, 1.13); Summary: Positive: aMED & odds of no CD; Positive: DASH & odds of no CD; Positive: AHEI-2010 & odds of no CD; Positive: PDI & odds of no CD; Positive: hPDI & odds of no CD | - Did not account for: SEP (marital status adjusted); - Diet assessment: FFQ assessed once at baseline; - Outcome measurement: MMSE (Singapore-modified) - No CD based on SM-MMSE using education-specific cut-points: ≥18 if no education, ≥21 for primary, or ≥25 for secondary school or higher education; Funding: Singapore National Medical Research Council; NCI/NIH; Saw Swee Hock School of Public Health, National University of Singapore
Zhu, 2022 ^83^; China; Chinese Longitudinal Healthy Longevity Survey (CLHS); Analytic N=6136; Participant characteristics:; - [underlined: Race and/or Ethnicity: NR] (majority Han Chinese); 19% Central, 36% Eastern, 7% Northeastern, 4% northern, 1% northwestern, 24% southern, 10% southwestern China; - [underlined: SEP]: 83% Rurual; 47% no formal education; 90% non-professional work; 60% finanancially dependent; 51% married; - [underlined: Selection:] Excluded those with baseline MMSE score <24 (abnormal CF) | - DP Age(s): 80 y (SD: 9.83) at baseline; - DP(s) examined: Plant-based diet index (PDI; healthful/unhealthful) [Satija, 2016]; - DP Components:; - PDI: Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Negative: Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; - hPDI: Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Negative: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; - uPDI: Negative: Whole grains; Fruits; Vegetables; Nuts; Legumes; Tea/coffee; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; Positive: Fruit juices & Veg. Oils; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; - DP Method(s): Index/Score; Comparisons: Categorical, quartiles (Q1, HR: 1 ref); linear trend of PDI, hPDI, uPDI | Follow-Up Duration: ∼10y; Results:; PDI; Q2, HR: 0.90, 95% CI: 0.81, 1.01; p=0.064; Q3, HR: 0.64, 95% CI: 0.57, 0.72; p<0.001; Q4, HR: 0.45, 95% CI: 0.39, 0.52; p<0.001; p-trend<0.001; hPDI; Q2, HR: 0.90, 95% CI: 0.81, 1.00; p=0.044; Q3, HR: 0.76, 95% CI: 0.67, 0.85; p<0.001; Q4, HR: 0.61, 95% CI: 0.54, 0.70; p<0.001; p-trend<0.001; uPDI; Q2, HR: 1.17, 95% CI: 1.03, 1.33; p=0.014; Q3, HR: 1.47, 95% CI: 1.30, 1.66; p<0.001; Q4, HR: 2.03, 95% CI: 1.79, 2.31; p<0.001; p-trend<0.001; Summary: Inverse: PDI & CD (odds of MMSE <24); Inverse: hPDI & CD (odds of MMSE <24); Positive: uPDI & CD (odds of MMSE <24) | - Did not account for: None (all); - Diet assessment: FFQ assessed once; - Outcome measurement: MMSE (<24 impairment; <18 for sensitivity test); Funding: National Natural Sciences Foundation of China; National Key R&D Program of China

Table 7 Risk of bias for randomized controlled trials examining dietary patterns consumed by adults and older adults and risk of cognitive decline, dementia, Alzheimer’s disease, and mild cognitive impairment^a^

Article | Randomization | Deviations from intended interventions (effect of assignment) or (per-protocol) | Missing outcome data | Outcome measurement | Selection of the reported result | Overall risk of bias
Barnes, 2023 ^1^ | LOW | LOW | LOW | LOW | LOW | LOW

a Possible ratings of low, some concerns, or high determined using the “Cochrane Risk-of-bias 2.0” (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2019 version)” ( Sterne JAC, Savović J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ 2019; 366: 14898. )

Table 8 Risk of bias for observational studies examining dietary patterns consumed by adults and older adults and risk of cognitive decline, dementia, Alzheimer’s disease, and mild cognitive impairment^*^ * Possible ratings of low, some concerns, high, very high, not applicable, or no information were determined using the "Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)" tool ( ROBINS-E Development Group, Higgins J, Morgan R, Rooney A . Risk Of Bias In Non-randomized Studies - of Exposure (ROBINS-E). Launch version, 1 June 2022. Available from: https://www.riskofbias.info/welcome/robins-e-tool. )

| Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall
Agarwal, 2021 ^3^ | High | Some concerns | Low | Low | Low | Some concerns | Some concerns | High
Andreu-Reinón, 2021 ^4^ | High | High | Low | Low | Low | Some concerns | Some concerns | High
Ashby-Mitchell 2015 ^5^ | High | Some concerns | Low | Low | High | Some concerns | High | High
Beydoun 2022 ^6^ | Some concerns | Some concerns | Low | Low | Some concerns | High | High | High
Boumenna, 2022 ^7^ | Low | Low | Low | Low | Low | Some concerns | Some concerns | Some concerns
Charisis, 2021 ^8^ | High | Some concerns | Low | Low | Some concerns | Low | Some concerns | High
Chen, 2017 ^14^ | Very high | Some concerns | Low | Low | Some concerns | Low | High | Very high
Chen, 2021 ^12^ | Some concerns | Some concerns | Low | Low | High | Some concerns | Some concerns | High
Chen, 2022 ^13^ | Some concerns | Some concerns | Low | Low | Some concerns | Some concerns | Some concerns | High
Chen 2023 ^10^ | Some concerns | Low | Low | Low | High | Some concerns | Some concerns | High
Chen, 2023 ^11^ | High | Some concerns | Some concerns | Low | Some concerns | Low | Some concerns | High
Chen, 2023 ^9^ | Some concerns | Some concerns | Low | Low | Low | High | Some concerns | High
Chou, 2019 ^15^ | High | Some concerns | Some concerns | Low | Some concerns | Low | Some concerns | High
Corley & Deary, 2021 ^16^ | Very high | Some concerns | Low | Low | Low | Some concerns | Low | Very high
Cornelis, 2023 ^17^ | Low | Low | Low | Low | Some concerns | High | High | High
D’Amico, 2020 ^18^ | Very high | Some concerns | Some concerns | Low | High | Some concerns | Some concerns | Very high
Daniel, 2021 ^19^ | Low | Some concerns | Some concerns | Low | Some concerns | Some concerns | High | High
de Crom, 2022 ^20^ | Some concerns | Some concerns | Low | Low | High | Low | Some concerns | High
de Crom 2023 ^21^ | High | High | Low | Low | Low | Low | Some concerns | High
Dhana, 2021 ^22^ | High | Low | Some concerns | Low | High | Some concerns | Some concerns | High
Flores, 2023 ^23^ | Low | Low | Low | Low | Some concerns | Low | Some concerns | Some concerns
Galbete, 2015 ^24^ | High | Some concerns | Some concerns | Low | Some concerns | High | Some concerns | High
Gelber 2012 ^25^ | High | Some concerns | Low | Low | Low | Low | Low | High
Glans, 2023 ^26^ | High | Some concerns | Low | Low | Low | Low | Some concerns | High
Granic, 2016 ^27^ | Some concerns | Some concerns | Low | Low | Some concerns | Low | Some concerns | High
Gregory 2022 ^28^ | High | Some concerns | Low | Low | High | High | Some concerns | High
Guo, 2021 ^29^ | Very high | High | Low | Low | High | Low | Some concerns | Very high
Hsiao, 2022 ^30^ | High | High | Low | Low | Low | Some concerns | Low | High
Hu, 2020 ^31^ | Some concerns | Some concerns | Some concerns | Low | Low | Some concerns | Some concerns | High
Jia, 2023 ^32^ | Some concerns | Some concerns | Low | Low | High | High | Some concerns | High
Keenan 2020 ^33^ | Very high | Some concerns | Low | Some concerns | Low | Some concerns | Low | Very high
Kjeldsen 2022 ^34^ | Low | Low | Low | Low | Low | High | Some concerns | High
Lai, 2023 ^35^ | Some concerns | Some concerns | Low | Low | Low | Some concerns | Some concerns | High
Larsson & Wolk, 2018 ^36^ | High | High | Low | Low | High | Low | Some concerns | High
Liang, 2022 ^37^ | High | Some concerns | Low | Low | Some concerns | Some concerns | Some concerns | High
Liu, 2022 ^38^ | Very high | Low | Low | Low | High | Some concerns | Some concerns | Very high
Lohman, 2023 ^39^ | High | Some concerns | Low | Low | Low | High | Low | High
Lu, 2021 ^40^ | High | Low | Low | Low | High | Some concerns | High | High
Malek, 2022 ^41^ | Low | Some concerns | Low | Low | Some concerns | Some concerns | Low | Some concerns
Mamalaki 2023 ^42^ | High | Some concerns | Low | Low | Low | Some concerns | High | High
Mattei, 2019 ^43^ | Low | Some concerns | Low | Low | Some concerns | Low | Some concerns | Some concerns
Melo van Lent, 2021 ^44^ | Some concerns | Low | Low | Low | High | Some concerns | Some concerns | High
Melo van Lent, 2022 ^45^ | Some concerns | Some concerns | Low | Low | Low | High | Some concerns | High
Milte, 2019 ^46^ | High | Some concerns | Low | Low | High | High | Some concerns | High
Morris, 2015 ^47^ | High | Low | Low | Low | Some concerns | Some concerns | Low | High
Morris, 2015 ^48^ | Very high | Some concerns | Low | Low | Some concerns | Low | Some concerns | Very high
Moustafa, 2022 ^49^ | Low | Some concerns | Low | Low | Low | Some concerns | Some concerns | Some concerns
Mueller, 2020 ^50^ | Very high | Some concerns | Low | Low | Some concerns | Some concerns | Low | Very high
Muñoz-Garcia, 2020 ^52^ | High | Some concerns | Low | Low | Low | High | Some concerns | High
Muñoz-Garcia, 2022 ^51^ | High | Some concerns | Low | Low | Low | High | Some concerns | High
Nicoli, 2021 ^53^ | High | Some concerns | Some concerns | Low | High | Low | Some concerns | High
Nishi 2021 ^54^ | Some concerns | Some concerns | Low | Low | Low | Some concerns | High | High
Nooyens, 2021 ^55^ | Some concerns | Some concerns | Low | Low | Low | Some concerns | Some concerns | High
Olsson, 2015 ^56^ | Very high | Some concerns | Low | Low | Low | Low | Low | Very high
Parrott, 2021 ^57^ | High | Some concerns | Low | Low | Some concerns | Some concerns | Some concerns | High
Razquin, 2022 ^58^ | Very high | Some concerns | Low | Low | Low | High | Some concerns | Very high
Rodrigues, 2020 ^59^ | Some concerns | Some concerns | Low | Low | Some concerns | Some concerns | Some concerns | High
Sameulsson, 2021 ^60^ | Some concerns | Some concerns | Low | Low | Some concerns | Low | Some concerns | High
Shang, 2021 ^61^ | Some concerns | Low | Low | Low | Low | Some concerns | High | High
Shannon, 2023 ^62^ | Some concerns | High | Low | Low | Some concerns | High | Some concerns | High
Tanaka, 2018 ^63^ | High | Some concerns | Low | Low | Some concerns | Some concerns | Some concerns | High
Tangney, 2014 ^64^ | Very high | Some concerns | Low | Low | Low | Some concerns | Some concerns | Very high
Thomas, 2024 ^65^ | Very high | Low | Low | Low | Low | Low | Low | Very high
Tong, 2021 ^66^ | Some concerns | Some concerns | Some concerns | Low | High | Some concerns | Some concerns | High
Trichopoulou, 2015 ^67^ | Some concerns | Some concerns | Low | Low | High | Some concerns | Some concerns | High
van Soest 2023 ^68^ | Some concerns | Some concerns | Low | Some concerns | Some concerns | Some concerns | Some concerns | High
Vercambre, 2012 ^69^ | Low | Some concerns | Low | Some concerns | Low | Some concerns | Low | Some concerns
Vlachos, 2022 ^70^ | Very high | Some concerns | Some concerns | Low | Very high | Some concerns | Some concerns | Very high
Vu, 2022 ^71^ | Some concerns | High | Low | Low | High | High | High | High
Wade, 2021 ^72^ | High | Some concerns | Low | Low | Some concerns | Some concerns | Some concerns | High
Wagner, 2020 ^2^ | Very high | Low | Low | Low | Some concerns | High | Some concerns | Very high
Wagner, 2023 ^73^ | Very high | Some concerns | Low | Low | Some concerns | Some concerns | Some concerns | Very high
Wang, 2021 ^74^ | Low | Some concerns | Low | Low | Low | Some concerns | Some concerns | Some concerns
Wu, 2023 ^75^ | Low | Some concerns | Low | Low | Low | High | Some concerns | Some concerns
Yuan, 2022 ^76^ | Low | Low | Low | Low | Low | Some concerns | High | High
Zhang, 2021 ^81^ | Some concerns | Some concerns | Low | Low | High | Some concerns | High | High
Zhang 2023 ^78^ | Low | Some concerns | Low | Low | Low | Some concerns | Some concerns | Some concerns
Zhang 2023 ^80^ | Low | Some concerns | Low | Low | Some concerns | High | High | High
Zhang 2023 ^77^ | Low | Low | Low | Low | Low | High | Some concerns | High
Zhang 2023 ^79^ | Some concerns | Some concerns | Low | Low | Low | Some concerns | Low | Some concerns
Zhou 2021 ^82^ | Some concerns | Some concerns | Some concerns | Low | Low | Some concerns | Some concerns | High
Zhu, 2022 ^83^ | Low | Some concerns | Low | Low | Some concerns | Some concerns | Some concerns | High