# Plain-language summary

### What is the question?

The question is: What is the relationship between dietary patterns consumed and risk of cognitive decline, dementia, Alzheimer's disease, and mild cognitive impairment? The population of interest for this question include children and adolescents, and adults and older adults at intervention/exposure, and adults and older adults at outcome.

### Why was this question asked?

This systematic review was conducted by the 2025 Dietary Guidelines Advisory Committee as part of the process to develop the Dietary Guidelines for Americans, 2025–2030.

### How was this question answered?

The Committee conducted a systematic review to answer this question with support from the USDA Nutrition Evidence Systematic Review team. This review updated an existing review that was conducted by the Dietary Patterns Subcommittee of the 2020 Dietary Guidelines Advisory Committee.

### What is the answer to the question?

Dietary patterns consumed by adults and older adults that are characterized by higher intakes of vegetables, fruits, legumes or beans, nuts, fish and/or seafood, and unsaturated vegetable oils/fats and lower in red and processed meats and sugar-sweetened beverages, are associated with lower risk of age-related cognitive decline, mild cognitive impairment, dementia and/or Alzheimer's disease. This conclusion statement is based on evidence graded as moderate.

### How up-to-date is this systematic review?

The conclusion statement from this review is based on articles published between March 2020 and January 2024, as well as studies that were excluded from prior reviews but met the updated inclusion criteria.