# Appendix 6 Dietary pattern visualization

The Committee’s synthesis was facilitated by data visualization tables that presented the dietary pattern components in each of the dietary patterns examined in the body of evidence. During evidence synthesis, these tables were used in conjunction with other materials to compare and contrast the components between and within the dietary patterns studied along with the direction, magnitude, and statistical significance of reported results. Detailed information about the body of evidence, including study and population characteristics, reported results for all relevant outcomes, key confounders accounted for, study limitations, and funding sources, are summarized in the evidence tables of this report (Table 6).

Each column represents the most commonly reported foods/food groups or nutrients across dietary patterns in this body of evidence. Two additional columns, “Other, A” and “Other, B”, captured a variety of other components less frequently reported across dietary patterns that did not fit into one of the preceding columns or categories, such as fast and/or fried food, pizza, snacks, and sofritas. Multiple symbols in each cell mean that the dietary pattern included multiple components from that column/category. Empty cells mean that the dietary pattern did not describe a component within that column/category.

Table A 8 Visualization of dietary pattern components across dietary patterns consumed by adults and older adults organized alphabetically by first-author last name across evidence examining the relationship between dietary patterns consumed and risk of cognitive decline, dementia, Alzheimer’s disease, and mild cognitive impairment^*^ * ▲ Positively-scored component, reflecting higher intake within the food category as part of the pattern; ▼ Negatively-scored component, reflecting lower intake within the food category as part of the pattern; ◄ Neutral component, reflecting moderate (in contrast to higher or lower) intake within the food category as part of the pattern ,^†^ † Abbreviations: AF, added fat; Al, alcohol; AP, animal-based foods and products; AS, added sugar; B, butter; Be, beans; B/P, beef/pork; C, coffee only; ch, cheese; CT, cereals and/or tubers; D, included with total dairy; DP, dietary pattern; FF, fried potato or French fries; F, fast and/or fried food; Fr, included with Fruit component; FS, fish and seafood; FV, fruits and/or vegetables; G, included with total grains or cereals; L, liquor; LN, legumes and nuts; LP, lean protein (total/foods); M, meat and or meat products; M:E, ratio of meat to eggs; Mi, milk; Med, Mediterranean; Na+, sodium; OF, oily and/or fatty fish; oo, olive oil; Or, organs/organ meat; P, processed; PCA, principal component analysis; pro, protein (total/foods); R, red meat; RP, red and/or processed; RRR, reduced rank regression; rw, red wine; S, soy and/or soy products; SB, sugar-sweetened beverage; SD, ‘sugary dairy’; SN, soybeans and nuts; T, tea only; TC, tea and/or coffee; Tr, trans fat; UF: SF, ratio of unsaturated relative to saturated fat; vo, vegetable oils; V, included in vegetables group; VL, vegetables and legumes; W, wine; W/B, whole grains and mixed beans; X, not included; y, yogurt

Article; Approach^‡^; ‡ Dietary approaches included methods such as a priori index/score analysis and investigator-assigned dietary intervention (RCT), a posteriori principal component analysis (PCA), and reduced rank regression (RRR). The dietary pattern is abbreviated in this table due to limited space but is described in more detail in Table 6 of the main document.; ; Dietary pattern | Vegetables | Potato | Legumes | Fruit | Fruit Juice | Nuts, Seeds | Grains: Whole | Grains | Grains: Refined | Fish | Seafood, shellfish | Meats (Red Processed) | Lean meats (Poultry) | Eggs | Dairy | Dairy: Low, non-fat | Dairy: Whole, high fat | Sugary Beverages | Sugary foods | Fat: Unsaturated | Fat: Other | Fat: Saturated | Alcohol | Salty foods, Sodium Na^+^ | Tea and Coffee | Fiber | Other, A | Other, B
Barnes, 2023; RCT; MIND v. Control diet | ▲ | | ▲ | ▲ | | ▲ | ▲ | | | ▲ | FS | ▼ R | ▲ | | ▼ ch | | | | ▼ | ▲ oo | | ▼ B | ▲ W | | | | ▼ F
Agarwal, 2021; a priori; MedDietScore | ▲ | ▲ | ▲ | ▲ | | | ▲ | | | ▲ | | ▼ RP | ▼ | | | | ▼ | | | ▲ oo | | | ▼
Agarwal, 2021; PCA; ‘Western’ | | | | | | | | | ▲ | | | ▲ RP | | | | | ▲ | | ▲ | | | | | | | | ▲ F | ▲
Andreu-Reinón, 2021; a priori; rMED | ▲ | X | ▲ | ▲ | | Fr | G | ▲ | G | ▲ | | ▼ RP ▼ M | M | | | | | | | ▲ oo | | | ◀
Andreu-Reinón, 2021; a priori; MDS | ▲ | | ▲ | ▲ | | ▲ | | ▲ | | ▲ | | ▼ | | | ▼ | D | D | | | ▲ UF:SF | | UF:SF | ◀
Andreu-Reinón, 2021; a priori; aMED | ▲ | X | ▲ | ▲ | | ▲ | ▲ | | | ▲ | | ▼ RP | | | | | | | | ▲ UF :SF | | UF: SF | ◀
Andreu-Reinón, 2021; a priori; arMED | ▲ | X | ▲ | ▲ | | Fr | | ▲ | | ▲ | | ▼ M | M | | ▼ | D | D | | | ▲ oo
Ashby-Mitchell, 2015; PCA; ‘101, DP1’ | ▲ | ▲ | | ▲ | | | ▲ | ▲
Ashby-Mitchell, 2015; PCA; ‘101, DP2’ | | ▲ | | | | | | | | | | ▲ P | | | | | | | ▲ | | | | | | | | ▲ | ▲
Ashby-Mitchell, 2015; PCA; ‘101, DP3’ | ▲ | | | | | | | | ▼ | | | | | | ▲y | | | | ▼ | | | | | | | | ▼
Ashby-Mitchell, 2015; PCA; ‘101, DP4’ | | | | | | | | | | | | ▲ | ▲ | | ▲ ch | | | | | | | | | | | | ▲
Ashby-Mitchell, 2015; PCA; ‘101, DP5’ | ▲ | | ▲ | ▲ | | | | | | ▲ | | | | | ▲ ch | | | | | | | | | | | | ▲ S
Ashby-Mitchell, 2015; PCA; ‘101, DP6’ | ▼ | | | | | | ▲ | | ▲ | | | | | | | | | | | | | | ▲ W, L
Ashby-Mitchell, 2015; PCA; ‘101, DP7’ | | | | ▲ | ▲ | | ▲ | ▲ | ▲ | | | | | ▼ | | ▲ | ▼ | | | | ▼ | ▼
Ashby-Mitchell, 2015; PCA; ‘32, DP1’ | | ▲ FF | | | | | | | ▲ | | | ▲ R | ▲ | | | | | | | | | | ▲ B | | | | ▲ | ▲
Ashby-Mitchell, 2015; PCA; ‘32, DP2’ | ▲ | | | ▲ | | ▲ | | | | ▲
Ashby-Mitchell, 2015; PCA; ‘32, DP3’ | ▲ | ▲ | | | | | ▲ | | | | | | | | | | | | | | | | ▼ W | | | | ▲
Ashby-Mitchell, 2015; PCA; ‘32, DP4’ | | | | | | | | | | | | | | ▲ | | ▼ | ▲ | | | | ▼ | ▲
Ashby-Mitchell, 2015; PCA; ‘20, DP1’ | ▲ | | | ▲ | ▲ | ▲ | ▲ | | | ▲ | | ▲ M | M | | | | | | | | | | | | | | ▲
Ashby-Mitchell, 2015; PCA; ‘20, DP2’ | | ▲ FF | ▼ | | | | | | | | | | | | | | | | ▲ | ▲ | ▲ | | | | | | ▲ | ▲
Ashby-Mitchell, 2015; PCA; ‘20, DP3’ | | | | | | | ▼ | | ▲ | | | ▲ M | M | | ▼ | | | | | | | | ▲
Beydoun, 2022; a priori; HEI-1995 | ▲ | | | ▲ | | | | ▲ | | | | ▼ M | M | | ▼ Mi | Mi | Mi | | | ▼ | ▼ | ▼ | | ◀ | | | ▲
Boumenna, 2022; a priori; MIND | ▲ | | ▲ Be | ▲ | | ▲ | ▲ | | | ▲ FS | FS | ▼ R | ▲ | | ▼ ch | | | | ▼ | ▲ oo | | ▼ B | ▲ W | | | | ▼ F
Charisis, 2021; MedDietScore | ▲ | ▲ | ▲ | ▲ | | | ▲ | | | ▲ | | ▼ RP | ▼ | | | | ▼ | | | ▲ oo | | | ▼
Chen, 2017; PCA; ‘Vegetable’ DP | ▲ | ▲ | | | | | | | | | | | | | | | | | | ▲
Chen, 2021; a priori; DGI-2013 | ▲ | | ▲ | ▲ | | ▲ | ▲ | | | ▲ | | | ▲ | ▲ | ▲ | | ▼ | | ▼ | ▼ | | ▼ | ▼ | ▼ | | | ▼
Chen, 2022; a priori; MDS | ▲ | | ▲ | ▲ | | ▲ | | ▲ | | ▲ | | ▼ RP | | | ▼ | D | D | | | ▲ UF:SF | | UF:SF | ◀
Chen, 2022; a priori; MedDietScore | ▲ | ▲ | ▲ | ▲ | | | ▲ | | | ▲ | | ▼ RP | ▼ | | | | ▼ | | | ▲ oo | | | ▼
Chen, 2022; a priori; mDASH | ▲ | X | ▲ LN | ▲ | Fr | LN | ▲ | | | | | ▼ RP | | | | ▲ | | ▼ | AS | | | | | ▼
Chen H, 2023; a priori; MIND | ▲ | | ▲ Be | ▲ | | ▲ | ▲ | | | ▲ FS | FS | ▼ R | ▲ | | ▼ ch | | | | ▼ | ▲ oo | | ▼ B | ▲ W | | | | ▼ F
Chen LW, 2023; a priori; mAHEI | ▲ | | | ▲ | | | ▲ | | | ▲ | | ▲ M:E | M:E | M:E | | | | | | | | | ◀ | | | | ▲ S | ▼ F
Chen J, 2023; PCA; ‘Traditional Finnish’ | | ▲ | | | ▼ | | | ▲ | | | | ▲ P | | | ▲ | | | | | | | ▲ | | | ▲
Chen J, 2023; PCA; ‘Vegetables and Dairy Products’ | ▲ | | | | | | | | | | | | | | ▲
Chen J, 2023; PCA; ‘Traditional Finnish & High Carbohydrate’ | | ▲ | | | | | | ▲ | | | | | | | | | | | ▲ | ▲ | ▲ | ▲
Chen J, 2023; PCA; ‘Red Meat’ | | | | | | | | | | ▲ | | ▲ | ▲ | ▲ | | | | | | | | | | | | | ▲
Chen J, 2023; PCA; ‘Healthy’ | ▲ | | ▲ LN | ▲ | | LN | | | | ▲ | | | | | ▲ ch | | | | | | | | | | ▲ T
Chen J, 2023; PCA; ‘High Carbohydrate’ | | ▲ | | ▲ | | | | ▲ | | | | ▲ M | M | ▲ | ▲ | | | | ▲ | ▲ | ▲
Chou, 2019; a priori; mAHEI | ▲ | | | ▲ | | | ▲ | | | ▲ | | ▲ M:E | M:E | M:E | | | | | | | | | ◀ | | | | ▲ S | ▼ F
Corley & Deary, 2021; a priori; MDS | ▲ | | ▲ | ▲ | | ▲ | | ▲ | | ▲ | | ▼ RP | | | ▼ | D | D | | | ▲ UF:SF | | UF:SF | ◀
Corley & Deary, 2021; PCA; ‘Mediterranean-Style’ | ▲ | | ▲ | | | | | ▲ | | ▲ | | | ▲ | | | | | | | ▲ oo | | | | | | | ▲ | ▲
Corley & Deary, 2021; PCA; ‘Traditional | ▲ | ▲ | ▲ | | | | | | | | | ▲ P | ▲ | | ▲ | | | | ▲ | | | | | | ▼ C | | ▲
Cornelis, 2023; a priori; MIND | ▲ | | ▲ Be | ▲ | | ▲ | ▲ | | | ▲ FS | FS | ▼ R | ▲ | | ▼ ch | | | | ▼ | ▲ oo | | ▼ B | ▲ W | | | | ▼ F
Cornelis, 2023; a priori; AHEI-2010 | ▲ | X | ▲ LN | ▲ | SB | LN | ▲ | | | ▲ OF | OF | ▼ RP | | | | | | ▼ | | | ▼ Tr | | ◀ | ▼
D’Amico, 2020; PCA; ‘Prudent ♂’ | ▲ | | ▲ | ▲ | | ▲ | ▲ | ▲ | | ▲ OF | | | ▲ | | | ▲ | | | | | | | | | | | ▲
D’Amico, 2020; PCA; ‘Western ♀’ | | ▲ | | | | | | | ▲ | | | ▲ RP | ▲ | ▲ | | | ▲ | ▲ | ▲ | | | ▲ | | ▲ | | | ▲ F
D’Amico, 2020; PCA; ‘Prudent ♀’ | ▲ | | ▲ | ▲ | | ▲ | | ▲ | | ▲ OF | | | | ▲ | ▲ ch | ▲ | | | | | | | | | | | ▲
D’Amico, 2020; PCA; ‘Western ♀’ | | ▲ | | | | | | ▲ | ▲ | | | ▲ RP | ▲ | | | | ▲ | ▲ | ▲ | | | ▲ | | ▲ | | | ▲ F
Daniel, 2021; a priori; DASH | ▲ | X | ▲ LN | ▲ | Fr | LN | ▲ | | | | | ▼ RP | | | | ▲ | | ▼ | | | | | | ▼
de Crom, 2022; a priori; MIND | ▲ | | ▲ Be | ▲ | | ▲ | ▲ | | | ▲ FS | FS | ▼ R | ▲ | | ▼ ch | | | | ▼ | ▲ oo | | ▼ B | ▲ W | | | | ▼ F
de Crom, 2022; a priori; DDG-2015 | ▲ | | ▲ | ▲ | | ▲ | ▲ | | ▼ | ▲ | | ▼ RP | | | ▲ | D | D | | | ▲ | | | ▼ | ▼ | ▲
de Crom, 2022; a priori; MedDietScore | ▲ | ▲ | ▲ | ▲ | | | ▲ | | | ▲ | | ▼ RP | ▼ | | | | ▼ | | | ▲ oo | | | ▼
de Crom, 2023; a priori; aPDI | ▲ | ▲ | ▲ | ▲ | | ▲ | ▲ | | ▲ | ▼ | FS | ▼ RP | ▼ | ▼ | ▼ ch, SD | ▼ | ▼ | ▲ | ▲ | ▲ vo | | ▼ | | | ▲ TC
de Crom, 2023; a priori; hPDI | ▲ | ▼ | ▲ | ▲ | | ▲ | ▲ | | ▼ | ▼ | FS | ▼ RP | ▼ | ▼ | ▼ ch, SD | ▼ | ▼ | ▼ | ▼ | ▲ vo | | ▼ | | | ▲ TC
de Crom, 2023; a priori; uPDI | ▼ | ▲ | ▼ | ▼ | | ▼ | ▼ | | ▲ | ▼ | FS | ▼ RP | ▼ | ▼ | ▼ ch, SD | ▼ | ▼ | ▲ | ▲ | ▲ vo | | ▼ | | | ▼ TC
Dhana, 2021; a priori; MIND | ▲ | | ▲ Be | ▲ | | ▲ | ▲ | | | ▲ FS | FS | ▼ R | ▲ | | ▼ ch | | | | ▼ | ▲ oo | | ▼ B | ▲ W | | | | ▼ F
Flores, 2023; a priori; DST | ▲ | | | ▲ | Fr | | G | ▲ | G | LP | LP | ▼ P | ▲ LP | | ◀ | | | | ▼ | | ▼ AF | | ▼ | | | | ▲
Galbete, 2015; a priori; MDS | ▲ | | ▲ | ▲ | | ▲ | | ▲ | | ▲ | | ▼ RP | | | ▼ | D | D | | | ▲ UF :SF | | UF: SF | ◀
Gelber, 2012; a priori; Diet Score | ▲ | | | ▲ | | | G | ▲ | G | ▲ | | ▼ M | M | | ▼ | D | D | | | ▲ UF:SF | | UF:SF | ◀
Glans, 2023; a priori; mMDS | ▲ VL | | VL | ▲ | | ▲ | | | | ▲ | ▲ | ▼ RP | | | | | | ▼ | ▼ | ▲ vo | ▼ | ▼ B | ▲ W
Glans, 2023; a priori; SDGS | ▲ FV | | | FV | | | | | | ▲ FS | FS | ▼ RP | | | | | | | ▼ | | | | | | | ▲
Granic, 2016; PCA; ‘High Red Meat’ | | ▲ | ▲ | | | | | | | | | ▲ | | | | | | | | ▲ | | ▼ | | | | | ▲
Granic, 2016; PCA; ‘Low Meat’ | | ▼ | | ▲ | | ▲ | ▲ | | | ▲ FS | FS | ▼ RP | | ▲ | | ▲ | ▲ | | | | | ◀ B | ▲ C, Al | | C, Al | | ▼ | ▲
Granic, 2016; PCA; ‘High Butter’ | | | | | | | | | | | | ◀ R | | | | | | | | ▼ | ▼ | ▲ B
Gregory, 2022; a priori; MEDAS | ▲ | | ▲ | ▲ | | ▲ | | | | ▲ | | ▼ R | ▲ | | ▼ | D | D | ▼ | ▼ | ▲ oo | | ▼ | ▲ rw | | | | ▲
Guo, 2021; a priori; AHA-LS7 | ▲ FV | | | FV | | | | | | ▲ | | | | | | | | | ▼ | | | | | ▼
Hsiao, 2022; a priori; DVS | ▲ | | ▲ | ▲ | | | | | | ▲ | ▲ | ▲ | ▲ | | ▲ | | | | | | | | | | ▲ T
Hu, 2020; a priori; HEI-2015 | ▲ | V | V | ▲ | | | ▲ | | ▼ | ▲ pro | pro | pro | pro | | ▲ | | | AS | ▼ | ▲ UF:SF | | ▼ | | ▼
Hu, 2020; a priori; AHEI-2010 | ▲ | | ▲ LN | ▲ | SB | LN | ▲ | | | | | ▼ RP | | | | | | ▼ | | ▲ UF:SF | ▼ TF | UF: SF | ◀ | ▼
Hu, 2020; a priori; aMED | ▲ | | ▲ | ▲ | | ▲ | ▲ | | | ▲ | | ▼ RP | | | | | | | | ▲ UF:SF | | UF:SF | ◀
Hu, 2020; a priori; DASH | ▲ | X | ▲ LN | ▲ | Fr | LN | ▲ | | | | | ▼ RP | | | | ▲ | | ▼ | | | | | | ▼
Jia, 2023; a priori; CDGI 2022-E | ▲ | G | W/B | ▲ | | ▲ | ▲ W/B | ◀ | | ◀ FS | FS | ◀ M, P | M, P | ◀ | ▲ | | | | | ▼ | | | ▼ | ▼
Keenan, 2020; a priori; aMED | ▲ | | ▲ | ▲ | | ▲ | ▲ | | | ▲ | | ▼ RP | | | | | | | | ▲ UF:SF | | UF:SF | ◀
Kjeldsen, 2022; a priori; Danish DG | ▲ | | | ▲ | | | | | | ▲ | | ▼ P | | | | | | ▼ | | ▲ | | ▼ | | | | | ▼ F
Lai, 2023; a priori; DASH | ▲ | X | ▲ LN | ▲ | Fr | LN | ▲ | | | | | ▼ RP | | | ▲ | D | D | ▼
Larsson & Wolk, 2018; a priori; DASH | ▲ | X | ▲ LN | ▲ | Fr | LN | ▲ | | | | | ▼ RP | | | | ▲ | | ▼
Larsson & Wolk, 2018; a priori; mMED | ▲ | | ▲ LN | ▲ | | LN | ▲ | | | ▲ | | ▼ RP | | | | | ▼ | | | ▲ oo | | | ◀
Liang, 2022; a priori; hPDI | ▲ | ▼ | ▲ | ▲ | ▼ | ▲ | ▲ | | ▼ | ▼ FS | FS | ▼ | M | ▼ | ▼ | | | ▼ | ▼ | ▲ | | ▼ | | | ▲ TC | | ▼ AP
Liang, 2022; a priori; PDI | ▲ | ▲ | ▲ | ▲ | ▲ | ▲ | ▲ | | ▲ | ▼ FS | FS | ▼ | M | ▼ | ▼ | | | ▲ | ▲ | ▲ | | ▼ | | | ▲ TC | | ▼ AP
Liang, 2022; a priori; uPDI | ▼ | ▲ | ▼ | ▼ | SB | ▼ | ▼ | | ▲ | ▼ FS | FS | ▼ | M | ▼ | ▼ | | | ▲ | ▲ | ▼ | | ▼ | | | ▼ TC | | ▼ AP
Liu, 2022; a priori; PDI | ▲ | ▲ | ▲ | ▲ | ▲ | ▲ | ▲ | | ▲ | ▼ FS | F style="background-color:#F79B85"S | ▼ | M | ▼ | ▼ | | | ▲ | ▲ | ▲ | | ▼ | | | ▲ TC | | ▼ AP
Liu, 2022; a priori; hPDI | ▲ | ▼ | ▲ | ▲ | ▼ | ▲ | ▲ | | ▼ | ▼ FS | FS | ▼ | M | ▼ | ▼ | | | ▼ | ▼ | ▲ | | ▼ | | | ▲ TC | | ▼ AP
Liu, 2022; a priori; uPDI | ▼ | ▲ | ▼ | ▼ | SB | ▼ | ▼ | | ▲ | ▼ FS | FS | ▼ | M | ▼ | ▼ | | | ▲ | ▲ | ▼ | | ▼ | | | ▼ TC | | ▼ AP
Lohman, 2023; a priori; HEI-2015 | ▲ | V | V | ▲ | | | ▲ | | ▼ | ▲ pro | pro | pro | pro | | ▲ | | | AS | ▼ | ▲ UF:SF | | ▼ | | ▼
Lu, 2021; a priori; JDI | ▲ | | | | | | | ▲ rice | | ▲ | | ▲ B/P | B/P | | | | | | | | | | | | ▲ TC | | ▲
Malek, 2022; PCA; ‘Sweet foods-beverages’ | | | | | | | | | | | | | | | ▲ SD | ▼ | | | ▲ | | | ▼ B | | | ▲ TC | | ▲
Malek, 2022; PCA; ‘Tropical fruits-oats’ | | | | ▲ | | | ▲
Malek, 2022; PCA; ‘Meat-vegetables-rice and noodles’ | ▲ | | | | | | | ▲ | ▲ | | | ▲ B/P | B/P
Malek, 2022; PCA; ‘Local snacks-fish and seafoods-high-salt-foods’ | | | | | | | | | | ▲ FS | FS | | | | | | | | | | | | | ▲ | | | ▲ | ▲
Malek, 2022; PCA; ‘Fruits-legumes’ | | | ▲ | ▲
Mamalaki, 2023; a priori; MedDietScore | ▲ | ▲ | ▲ | ▲ | | | ▲ | | | ▲ | | ▼ RP | ▼ | | | | ▼ | | | ▲ oo | | | ▼ W
Mattei, 2019; a priori; MDS | ▲ | | ▲ | ▲ | | ▲ | | ▲ | | ▲ | | ▼ RP | | | ▼ | D | D | | | ▲ UF:SF | | UF:SF | ◀
Mattei, 2019; a priori; HEI-2005 | ▲ | V | V, Be | ▲ | | | ▲ | ▲ | ▼ | | | ▲ M, Be | M, Be | | ▲ Mi, y, ch, S | Mi, y, ch, S | Mi, y, ch, S | AS, AF, Al | ▼ | ▲ | AF, AS, Al | ▼ | AF, AS, Al | ▼ Na+
Matteri, 2019; a priori; AHEI-2010 | ▲ | X | ▲ LN | ▲ | SB | LN | ▲ | | | | | ▼ RP | | | | | | ▼ | | ▲ UF:SF | ▼ Tr | UF:SF | ◀ | ▼
Mattei, 2019; a priori; DASH | ▲ | X | ▲ LN | ▲ | Fr | LN | ▲ | | | | | ▼ RP | | | | ▲ | | ▼ | | | | | | ▼
Melo van Lent, 2021; a priori; MIND | ▲ | | ▲ Be | ▲ | | ▲ | ▲ | | | ▲ FS | FS | ▼ R | ▲ | | ▼ ch | | | | ▼ | ▲ oo | | ▼ B | ▲ W | | | | ▼ F
Melo van Lent, 2022; a priori; EDIP | ▲ | | | | ▲ | | | | ▼ | ▼ | | ▼ P ▼ R ▼ Or | | | | | | ▼ | | | | | | | ▲ T ▲ C | | ▲
Milte, 2019; a priori; DGI-2013 | ▲ | | ▲ | ▲ | | ▲ | ▲ | | | ▲ | | | ▲ L | ▲ | ▲ | | ▼ | | ▼ | ▼ | | ▼ | ▼ | ▼ | | | ▼
Morris, 2015; a priori; MIND | ▲ | | ▲ Be | ▲ | | ▲ | ▲ | | | FS | ▲ | ▼ R | ▲ | | ▼ ch | | | | ▼ | ▲ oo | | ▼ B | ▲ W | | | | ▼ F
Morris, 2015 (MIND); a priori; MIND | ▲ | | ▲ Be | ▲ | | ▲ | ▲ | | | FS | ▲ | ▼ R | ▲ | | ▼ ch | | | | ▼ | ▲ oo | | ▼ B | ▲ W | | | | ▼ F
Moustafa, 2022; a priori; MDS | ▲ | | ▲ | ▲ | | ▲ | | ▲ | | ▲ | | ▼ RP | | | ▼ | D | D | | | ▲ UF:SF | | UF:SF | ◀
Moustafa, 2022; a priori; mMDS | ▲ | | ▲ | ▲ | | ▲ | ▲ | | | ▲ | | ▼ RP | | | ▼ | D | D | | | ▲ UF:SF | | UF:SF | ◀
Mueller, 2020; a priori; MIND | ▲ | | ▲ | ▲ | | ▲ | ▲ | | | FS | ▲ | ▼ R | ▲ | | ▼ ch | | | | ▼ | ▲ oo | | ▼ B | ▲ W | | | | ▼ F
Muñoz-García, 2020; a priori; MEDAS | ▲ | | ▲ | ▲ | | ▲ | | | | ▲ | | ▼ RP | ▲ | | | | | ▼ | ▼ | ▲ oo | | ▼ | ▲ rw | | | | ▲
Muñoz-García, 2020; a priori; MDS | ▲ | | ▲ | ▲ | | ▲ | | ▲ | | ▲ | | ▼ RP | | | ▼ | D | D | | | ▲ UF:SF | | UF:SF | ◀
Muñoz-García, 2020; a priori; DASH | ▲ | X | ▲ LN | ▲ | Fr | LN | ▲ | | | | | ▼ RP | | | | ▲ | | ▼ | | | | | | ▼
Muñoz-García, 2020; a priori; MIND | ▲ | | ▲ Be | ▲ | | ▲ | ▲ | | | FS | ▲ | ▼ R | ▲ | | ▼ ch | | | | ▼ | ▲ oo | | ▼ B | ▲ W | | | | ▼ F
Muñoz-García, 2020; a priori; AHEI-2010 | ▲ | X | ▲ LN | ▲ | SB | LN | ▲ | | | | | ▼ RP | | | | | | ▼ | | ▲ UF:SF | ▼ Tr | UF:SF | ◀ | ▼
Muñoz-García, 2020; a priori; Provegetaria n Food Pattern | ▲ | ▲ | ▲ | ▲ | | ▲ | | ▲ | | ▼ | FS | ▼ M | M | | ▼ | D | D | | | | | ▼
Muñoz-García, 2022; PCA; ‘Western’ | | | | | | | | | ▲ | | | ▲ RP | | ▲ | | | ▲ | ▲ | ▲ | | | | | | | | ▲ F | ▲
Muñoz-García, 2022; PCA; ‘Mediterranean’ | ▲ | | | ▲ | ▲ | ▲ | | | | ▲ | | | | | | | | | | ▲ oo
Nicoli, 2021; a priori; MDS | ▲ | | ▲ | ▲ | | ▲ | | ▲ | | ▲ | | ▼ RP | | | ▼ | D | D | | | ▲ UF:SF | | UF:SF | ◀
Nishi, 2021; a priori; MEDAS | ▲ | | ▲ | ▲ | | ▲ | | | | ▲ | | ▼ RP | ▲ | | | | | ▼ | ▼ | ▲ oo | | ▼ | ▲ rw | | | | ▲
Nishi, 2021; a priori; MIND | ▲ | | ▲ Be | ▲ | | ▲ | ▲ | | | FS | ▲ | ▼ R | ▲ | | ▼ ch | | | | ▼ | ▲ oo | | ▼ B | ▲ W | | | | ▼ F
Nishi, 2021; a priori; DASH | ▲ | X | ▲ LN | ▲ | Fr | LN | ▲ | | | | | ▼ RP | | | | ▲ | | ▼ | | | | | | ▼
Nooyens, 2021; a priori; mMDS | ▲ | | ▲ | ▲ | | ▲ | | ▲ | | ▲ | | ▼ RP | | | ▼ | D | D | | | ▲ UF:SF | | UF:SF | ◀
Nooyens, 2021; a priori; mDHD15 | ▲ | | ▲ | ▲ | ▼ | ▲ | ▲ | | | ▲ | | ▼ RP | | | ▲ | D | D | ▼ | | ▼ | AF | AF | ▼ | | ▲ T
Olsson, 2015; a priori; MDS | ▲ | | ▲ | ▲ | | ▲ | | ▲ | | ▲ | | ▼ RP | | | ▼ | D | D | | | ▲ UF:SF | | UF:SF | ◀
Parrott, 2021; PCA; ‘Prudent’ | ▲ | | ▲ | ▲ | | ▲ | ▲ | | | ▲ | FS | | ▲ | | | ▲ | | | | | | | | | | | ▲
Parrott, 2021; PCA; ‘Western’ | | ▲ | | | | | | | ▲ | | | ▲ RP | | | | | | ▲ | ▲ | | | ▲ B
Razquin, 2022; a priori; MDS | ▲ | | ▲ | ▲ | | ▲ | | ▲ | | ▲ | | ▼ RP | | | ▼ | D | D | | | ▲ UF:SF | | UF:SF | ◀
Rodrigues, 2020; a priori; MEDAS | ▲ | | ▲ | ▲ | | ▲ | | | | ▲ | | ▼ RP | ▲ | | | | | ▼ | ▼ | ▲ oo | | ▼ | ▲ rw | | | | ▲
Samuelsson, 2022; RRR; ‘Western’ | ▼ | ▲ | ▼ | ▼ | | ▼ | | | ▲ | | | ▲ P, M | P, M | | ▲ | ▼ | ▲ | | ▲ | | ▲ | | ▲
Samuelsson, 2022; RRR; ‘Healthy’ | ▲ | ▲ | | ▲ | ▲ | ▲ | ▲ | ▲ | | ▲ | ▲ | ▲ P, M | P, M | ▲ | ▲ | | | | ▲ | ▲ vo | ▲ | | ▲
Shang, 2021; PCA; ‘Dairy-fruits-fast foods’ | | | | ▲ | | | | | | | | | | ▲ | ▲ | D | D | | | | | | | | | | ▲ F
Shang, 2021; PCA; ‘Grains-vegetables-pork’ | ▲ | | | | | | | | ▲ | | | | ▲
Shang, 2021; PCA; ‘Plant-based’ | | | ▲ | ▲ | | | ▲ | ▲ F | ▼ | | | | | | | | | | ▼
Shang, 2021; PCA; ‘Beans-mushroom’ | | | ▲ | | | | | | | | | | | | | | | | | | | | | | | | ▲ | ▲
Shang, 2021; PCA; ‘Beverages-nuts’ | | | | | | ▲ | | | | | | | ▲ | | | | | | | | | | | | | | ▲
Shannon, 2023; a priori; MEDAS | ▲ | | ▲ | ▲ | | ▲ | | | | ▲ | | ▼ RP | ▲ | | | | | ▼ | ▼ | ▲ oo | | ▼ B | ▲ W | | | | ▲
Shannon, 2023; a priori; PyrMDS | ▲ | ▼ | ▲ | ▲ | | ▲ | | ▲ | | ▲ | | ▼ R ▼ P | ▲ | ▲ | ▲ | D | D | AS | ▼ | ▲ oo | | | ▼
Tanaka, 2018; a priori; MDS | ▲ | | ▲ | ▲ | | ▲ | | ▲ | | ▲ | | ▼ RP | | | ▼ | D | D | | | ▲ UF:SF | | UF:SF | ◀
Tangney, 2014; a priori; MedDietScore | ▲ | ▲ | ▲ | ▲ | | | ▲ | | | ▲ | | ▼ RP | ▼ | | | | ▼ | | | ▲ oo | | | ▼
Tangney, 2014; a priori; aDASH | ▲ | X | ▲ LN | ▲ | Fr | LN | | ▲ | | | | ▼ RP | | | ▲ | D | D | | ▼ | ▼ | ▼ | ▼ | | ▼
Thomas, 2024; a priori; DAGI | ▲ | | ▲ | ▲ | | | ▲ | ▲ | G | ▲ | FS | ▲ M | M | | ▲ | D | D | ▼ | ▼ | | ◀ Tr | ◀ | ▼ | ◀ | | ▲ | ◀
Thomas, 2024; a priori; MIND | ▲ | | ▲ Be | ▲ | | ▲ | ▲ | | | FS | ▲ | ▼ R | ▲ | | ▼ ch | | | | ▼ | ▲ oo | | ▼ B | ▲ W | | | | ▼ F
Thomas, 2024; a priori; MDS | ▲ | | ▲ | ▲ | | ▲ | | ▲ | | ▲ | | ▼ RP | | | ▼ | D | D | | | ▲ UF:SF | | UF:SF | ◀
Tong, 2021; a priori; DASH | ▲ | X | ▲ LN | ▲ | Fr | LN | ▲ | | | | | ▼ RP | | | ▲ | D | D | ▼
Trichopoulou, 2015; a priori; MDS | ▲ | | ▲ | ▲ | | ▲ | | ▲ | | ▲ | | ▼ RP | | | ▼ | D | D | | | ▲ UF:SF | | UF:SF | ◀
van Soest, 2023; a priori; mPDI | ▲ | ▲ | ▲ | ▲ | ▲ | ▲ | ▲ | | ▲ | ▼ FS | FS | ▼ M | M | ▼ | ▼ | | | ▲ | ▲ | ▲ | | | | | ▲ TC | | ▼ AP
van Soest, 2023; a priori; mhPDI | ▲ | ▼ | ▲ | ▲ | ▼ | ▲ | ▲ | | ▼ | ▼ FS | FS | ▼ M | M | ▼ | ▼ | | | ▼ | ▼ | ▲ | | | | | ▲ TC | | ▼ AP
van Soest, 2023; a priori; muPDI | ▼ | ▲ | ▼ | ▼ | ▲ SB | ▼ | ▼ | | ▲ | ▼ FS | FS | ▼ M | M | ▼ | ▼ | | | ▲ | ▲ | ▼ | | | | | ▼ TC | | ▼ AP
Vercambre, 2012; a priori; MedDietScore | ▲ | ▲ | ▲ | ▲ | | | ▲ | | | ▲ | | ▼ RP | ▼ | | | | ▼ | | | ▲ oo | | | ▼ W
Vercambre, 2012; a priori; MDS | ▲ | | ▲ | ▲ | | ▲ | | ▲ | | ▲ | | ▼ RP | | | ▼ | D | D | | | ▲ UF:SF | | UF:SF | ◀
Vlachos, 2022; a priori; MedDietScore | ▲ | ▲ | ▲ | ▲ | | | ▲ | | | ▲ | | ▼ RP | ▼ | | | | ▼ | | | ▲ oo | | | ▼
Vu, 2022; a priori; MIND | ▲ | | ▲ Be | ▲ | | ▲ | ▲ | | | FS | ▲ | ▼ R | ▲ | | ▼ ch | | | | ▼ | ▲ oo | | ▼ B | ▲ W | | | | ▼ F
Wade, 2019; a priori; LitMDS | ▲ | | ▲ | ▲ | | Fr | | ▲ | | ▲ | | ▼ M | | | ▼ | D | D | | | ▲ oo | | | ◀
Wagner, 2020; a priori; aMED | ▲ | X | ▲ | ▲ | | ▲ | ▲ | | | ▲ | | ▼ RP | | | | | | | | ▲ UF:SF | | UF:SF | ◀
Wagner, 2023; a priori; MIND | ▲ | | ▲ Be | ▲ | | ▲ | ▲ | | | FS | ▲ | ▼ R | ▲ | | ▼ ch | | | | ▼ | ▲ oo | | ▼ B | ▲ W | | | | ▼ F
Wang, 2021; a priori; DP Score | ▲ | | | ▲ | | ▲ | | ▲ | | ▲ | | ▼ M | M | | | ▲ Mi | Mi | | ▼
Wu, 2023; a priori; PDI | ▲ | ▲ | ▲ | ▲ | ▲ | ▲ | ▲ | | ▲ | ▼ FS | FS | ▼ M | M | ▼ | ▼ | | | ▲ | ▲ | ▲ | | ▼ | | | ▲ TC | | ▼ AP
Wu, 2023; a priori; hPDI | ▲ | ▼ | ▲ | ▲ | ▼ | ▲ | ▲ | | ▼ | ▼ FS | FS | ▼ M | M | ▼ | ▼ | | | ▼ | ▼ | ▲ | | ▼ | | | ▲ TC | | ▼ AP
Wu, 2023; a priori; uPDI | ▼ | ▲ | ▼ | ▼ | ▲ SB | ▼ | ▼ | | ▲ | ▼ FS | FS | ▼ M | M | ▼ | ▼ | | | ▲ | ▲ | ▼ | | ▼ | | | ▼ TC | | ▼ AP
Yuan, 2022; a priori; aMED | ▲ | X | ▲ | ▲ | | ▲ | ▲ | | | ▲ | | ▼ RP | | | | | | | | ▲ UF :SF | | UF:SF | ◀
Yuan, 2022; a priori; DASH | ▲ | X | ▲ LN | ▲ | Fr | LN | ▲ | | | | | ▼ RP | | | | ▲ | | ▼ | | | | | | ▼
Yuan, 2022; a priori; AHEI-2010 | ▲ | X | ▲ LN | ▲ | SB | LN | ▲ | | | | | ▼ RP | | | | | | ▼ | | ▲ UF:SF | ▼ Tr | UF:SF | ◀ | ▼
Zhang, 2021; a priori; CDGI-2018 | ▲ | ▲ CT | ▲ SN | ▲ | | SN | | CT | | ◀ | FS | ◀ M | M | ◀ | ▲ | D | D | | | ▼ | | | ▼ W | ▼
Zhang JJ, 2023; a priori; PHD | ▲ | ◀ | ▲ | ▲ | | ▲ | ▲ | ▼ | ▼ | ▲ | | ▼ | ◀ | ◀ | | | ◀ | ▼ | ▼ | ▲ | | ▼
Zhang J, 2023; a priori; hPDI | ▲ | ▼ | ▲ | ▲ | ▼ | ▲ | ▲ | | ▼ | ▼ FS | FS | ▼ M | M | ▼ | ▼ | | | ▼ | ▼ | ▲ | | ▼ | | | ▲ TC | | ▼ AP
Zhang J, 2023; a priori; MDS | ▲ | | ▲ | ▲ | | ▲ | | ▲ | | ▲ | | ▼ RP | | | ▼ | D | D | | | ▲ UF :SF | | UF:SF | ◀
Zhang J, 2023; a priori; aRFS | ▲ | ▲ | ▲ | ▲ | ▲ | | ▲ | ▲ | | | | | ▲
Zhang J, 2023; a priori; MIND | ▲ | | ▲ Be | ▲ | | ▲ | ▲ | | | FS | ▲ | ▼ R | ▲ | | ▼ ch | | | | ▼ | X | | ▼ B | ▲ W | | | | ▼ F
Zhang S, 2023; a priori; wJD19 | ▲ | | ▲ | ▲ | | | | ◀ rice | | ▲ | FS | ▼ R | ▼ | | | | | | | | | | | | ▲ T | | ▲
Zhang S, 2023; a priori; JD18 | ▲ | | | | | | | ▲ rice | | ▲ | FS | ▼ R | ▼ | | | | | | | | | | | | ▲ T | | ▲
Zhang S, 2023; a priori; mJDI12 | ▲ | | ▲ | ▲ | | | | ▲ rice | | ▲ | FS | ▼ R | ▼ | | | | | | | | | | | | ▲ T | | ▲ | ▼ C
Zhang S, 2023; a priori; JDI | ▲ | | | | | | | ▲ rice | | ▲ | FS | ▼ R | ▼ | | | | | | | | | | | | ▲ T | | ▲ | ▼ C
Zhang X, 2023; a priori; hPDI | ▲ | | ▲ | ▲ | | ▲ | | | | ▲ | | | ▲ | | | | | | | ▲
Zhou, 2021; a priori; PDI | ▲ | ▲ | ▲ | ▲ | ▲ | ▲ | ▲ | | ▲ | ▼ FS | FS | ▼ M | M | ▼ | ▼ | | | ▲ | ▲ | ▲ | | ▼ | | | ▲ TC | | ▼ AP
Zhou, 2021; a priori; aMED | ▲ | X | ▲ | ▲ | | ▲ | ▲ | | | ▲ | | ▼ RP | | | | | | | | ▲ UF :SF | | UF:SF | ◀
Zhou, 2021; a priori; hPDI | ▲ | ▼ | ▲ | ▲ | ▼ | ▲ | ▲ | | ▼ | ▼ FS | FS | ▼ M | M | ▼ | ▼ | | | ▼ | ▼ | ▲ | | ▼ | | | ▲ TC | | ▼ AP
Zhou, 2021; a priori; DASH | ▲ | X | ▲ LN | ▲ | Fr | LN | ▲ | | | | | ▼ RP | | | | ▲ | | ▼ | | | | | | ▼
Zhou, 2021; a priori; AHEI-2010 | ▲ | X | ▲ LN | ▲ | SB | LN | ▲ | | | | | ▼ RP | | | | | | ▼ | | ▲ UF :SF | ▼ Tr | UF:SF | ◀ | ▼
Zhu, 2022; a priori; PDI | ▲ | ▲ | ▲ | ▲ | ▲ | ▲ | ▲ | | ▲ | ▼ FS | FS | ▼ M | M | ▼ | ▼ | | | ▲ | ▲ | ▲ | | ▼ | | | ▲ TC | | ▼ AP
Zhu, 2022; a priori; uPDI | ▼ | ▲ | ▼ | ▼ | ▲ SB | ▼ | ▼ | | ▲ | ▼ FS | FS | ▼ M | M | ▼ | ▼ | | | ▲ | ▲ | ▼ | | ▼ | | | ▼ TC | | ▼ AP
Zhu, 2022; a priori; hPDI | ▲ | ▼ | ▲ | ▲ | ▼ | ▲ | ▲ | | ▼ | ▼ FS | FS | ▼ M | M | ▼ | ▼ | | | ▼ | ▼ | ▲ | | ▼ | | | ▲ TC | | ▼ AP