# Appendix 5 Excluded articles

The following table lists the articles excluded after full-text screening for this systematic review question. At least one reason for exclusion is provided for each article, though this may not reflect all possible reasons. Information about articles excluded after title and abstract screening is available upon request.

Table A 7 List of excluded articles with rationale

Number | Citation | Rationale
1 | Adjibade, M.,Assmann, K. E.,Julia, C.,Galan, P.,Hercberg, S.,Kesse-Guyot, E. Prospective association between adherence to the MIND diet and subjective memory complaints in the French NutriNet-Santé cohort. J Neurol. 2019. 266:942–952. doi: 10.1007/s00415-019-09218-y 30706155 | Data overlap
2 | Agarwal, P.,Leurgans, S. E.,Agrawal, S.,Aggarwal, N. T.,Cherian, L. J.,James, B. D.,Dhana, K.,Barnes, L. L.,Bennett, D. A.,Schneider, J. A. Association of Mediterranean-DASH Intervention for Neurodegenerative Delay and Mediterranean Diets With Alzheimer Disease Pathology. Neurology. 2023. 100:e2259–e2268. doi: 10.1212/WNL.0000000000207176 36889921 | Data overlap
3 | Akbaraly, T. N.,Singh-Manoux, A.,Dugravot, A.,Brunner, E. J.,Kivimäki, M.,Sabia, S. Association of Midlife Diet With Subsequent Risk for Dementia. Jama. 2019. 321:957–968. doi: 10.1001/jama.2019.1432 30860560 | Data overlap
4 | Akbaraly, T. N.,Singh-Manoux, A.,Marmot, M. G.,Brunner, E. J. Education attenuates the association between dietary patterns and cognition. Dement Geriatr Cogn Disord. 2009. 27:147–54. doi: 10.1159/000199235 19182482 | Study design
5 | Akbaraly, T.,Sabia, S.,Hagger-Johnson, G.,Tabak, A. G.,Shipley, M. J.,Jokela, M.,Brunner, E. J.,Hamer, M.,Batty, G. D.,Singh-Manoux, A.,Kivimaki, M. Does overall diet in midlife predict future aging phenotypes? A cohort study. Am J Med. 2013. 126:411–419.e3. doi: 10.1016/j.amjmed.2012.10.028 23582933 | Outcome
6 | Allés, B.,Samieri, C.,Jutand, M. A.,Carmichael, P. H.,Shatenstein, B.,Gaudreau, P.Ferland, G.,Barberger-Gateau, P. Laurin, D. Nutrient Patterns, Cognitive Function, and Decline in Older Persons: Results from the Three-City and NuAge Studies. Nutrients. 2019. 11 (8):1808. doi: 10.3390/nu11081808 31387312 | Intervention/Exposure
7 | Almendrales Rangel, C.,Noble, Y.,Radd-Vagenas, S.,Mavros, Y.,Flood, V. M.,OĽeary, F.,Brodaty, H.,Sachdev, P. S.,Heffernan, M.,Valenzuela, M.,Anstey, K. J.,Daniel, K.,Ginige, J. A.,San Jose, J. C.,Chau, T.,Garnés Rancurello, S.,Fiatarone Singh, M. A.. Nutrition Module design in Maintain Your Brain: an internet-based randomised controlled trial to prevent cognitive decline and dementia. Br J Nutr. 2022. 127:1259–1268. doi: 10.1017/S0007114521001859 34078487 | Study design, Publication status
8 | An, Y.,Zhang, X.,Wang, Y.,Wang, Y.,Liu, W.,Wang, T.,Qin, Z.,Xiao, R. Longitudinal and nonlinear relations of dietary and Serum cholesterol in midlife with cognitive decline: results from EMCOAstudy. Mol Neurodegener. 2019. 14:51. doi: 10.1186/s13024-019-0353-1 31888696 | Intervention/Exposure
9 | Anastasiou, C. A.,Yannakoulia, M.,Kontogianni, M. D.,Kosmidis, M. H.,Mamalaki, E.,Dardiotis, E.,Hadjigeorgiou, G.,Sakka, P.,Tsapanou, A.,Lykou, A.,Scarmeas, N. Mediterranean Lifestyle in Relation to Cognitive Health: Results from the HELIAD Study. Nutrients. 2018. 10(10):1557. doi: 10.3390/nu10101557 30347812 | Data overlap
10 | Anastasiou, C. A.,Yannakoulia, M.,Kosmidis, M. H.,Dardiotis, E.,Hadjigeorgiou, G. M.,Sakka, P.,Arampatzi, X.,Bougea, A.,Labropoulos, I.,Scarmeas, N. Mediterranean diet and cognitive health: Initial results from the Hellenic Longitudinal Investigation of Ageing and Diet. PLoS One. 2017. 12:e0182048. doi: 10.1371/journal.pone.0182048 28763509 | Data overlap
11 | Arjmand, G.,Abbas-Zadeh, M.,Eftekhari, M. H. Effect of MIND diet intervention on cognitive performance and brain structure in healthy obese women: a randomized controlled trial. Sci Rep. 2022. 12:2871. doi: 10.1038/s41598-021-04258-9 35190536 | Outcome, Size of study groups
12 | Assmann, K. E.,Adjibade, M.,Adriouch, S.,Andreeva, V. A.,Julia, C.,Hercberg, S.,Galan, P.,Kesse-Guyot, E. Association of diet quality and physical activity with healthy ageing in the French NutriNet-Santé cohort. Br J Nutr. 2019. 122:93–102. doi: 10.1017/S0007114519000898 31162001 | Outcome
13 | Assmann, K. E.,Adjibade, M.,Andreeva, V. A.,Hercberg, S.,Galan, P.,Kesse-Guyot, E. Association Between Adherence to the Mediterranean Diet at Midlife and Healthy Aging in a Cohort of French Adults. J Gerontol A Biol Sci Med Sci. 2018. 73:347–354. doi: 10.1093/gerona/glx066 28460137 | Outcome
14 | Assmann, K. E.,Andreeva, V. A.,Camilleri, G. M.,Verger, E. O.,Jeandel, C.,Hercberg, S.,Galan, P.,Kesse-Guyot, E. Dietary scores at midlife and healthy ageing in a French prospective cohort. Br J Nutr. 2016. 116:666–76. doi: 10.1017/S0007114516002233 27301412 | Outcome
15 | Assmann, K. E.,Lassale, C.,Andreeva, V. A.,Jeandel, C.,Hercberg, S.,Galan, P.,Kesse-Guyot, E. A Healthy Dietary Pattern at Midlife, Combined with a Regulated Energy Intake, Is Related to Increased Odds for Healthy Aging. J Nutr. 2015. 145:2139–45. doi: 10.3945/jn.115.210740 26246320 | Outcome
16 | Assmann, K. E.,Ruhunuhewa, I.,Adjibade, M.,Li, Z.,Varraso, R.,Hercberg, S.,Galan, P.,Kesse-Guyot, E. The Mediating Role of Overweight and Obesity in the Prospective Association between Overall Dietary Quality and Healthy Aging. Nutrients. 2018. 10(4):515. doi: 10.3390/nu10040515 29677164 | Outcome
17 | Bajerska, J.,Woźniewicz, M.,Suwalska, A.,Jeszka, J. Eating patterns are associated with cognitive function in the elderly at risk of metabolic syndrome from rural areas. Eur Rev Med Pharmacol Sci. 2014. 18:3234–45 25487934 | Study design
18 | Barberger-Gateau, P.,Raffaitin, C.,Letenneur, L.,Berr, C.,Tzourio, C.,Dartigues, J. F.,Alpérovitch, A. Dietary patterns and risk of dementia: the Three-City cohort study. Neurology. 2007. 69:1921–30. doi: 10.1212/01.wnl.0000278116.37320.52 17998483 | Study design
19 | Bartlett, L.,Brady, J. J. R.,Farrow, M.,Kim, S.,Bindoff, A.,Fair, H.,Vickers, J. C.,Sinclair, D. Change in modifiable dementia risk factors during COVID-19 lockdown: The experience of over 50s in Tasmania, Australia. Alzheimers Dement (NY). 2021. 7:e12169. doi: 10.1002/trc2.12169 | Outcome
20 | Berendsen, A. A. M.,Kang, J. H.,van de Rest, O.,Feskens, E. J. M.,de Groot, Lcpgm,Grodstein, F.. The Dietary Approaches to Stop Hypertension Diet, Cognitive Function, and Cognitive Decline in American Older Women. J Am Med Dir Assoc. 2017. 18:427–432. doi: 10.1016/j.jamda.2016.11.026 28108204 | Data overlap
21 | Berendsen, A. A. M.,Kang, J. H.,Van De Rest, O.,Jankovic, N.,Kampman, E.,Kiefte-De Jong, J. C.,Franco, O. H.,Ikram, M. A.,Pikhart, H.,Nilsson, L. M.,Brenner, H.,Boffetta, P.,Rafnsson, S. B.,Gustafson, D.,Kyrozis, A.,Trichopoulou, A.,Feskens, E. J. M.,Grodstein, F.,De Groot, L. C. P. G. M.. Association of Adherence to a Healthy Diet with Cognitive Decline in European and American Older Adults: A Meta-Analysis within the CHANCES Consortium. Dementia and Geriatric Cognitive Disorders. 2017. 43:215–227. doi: 10.1159/000464269 28324877 | Study design
22 | Berendsen, A. M.,Kang, J. H.,Feskens, E. J. M.,de Groot, Cpgm,Grodstein, F.,van de Rest, O.. Association of Long-Term Adherence to the MIND Diet with Cognitive Function and Cognitive Decline in American Women. J Nutr Health Aging. 2018. 22:222–229. doi: 10.1007/s12603-017-0909-0.29380849 | Data overlap
23 | Berti, V.,Walters, M.,Sterling, J.,Quinn, C. G.,Logue, M.,Andrews, R.,Matthews, D. C.,Osorio, R. S.,Pupi, A.,Vallabhajosula, S.,Isaacson, R. S.,de Leon, M. J.,Mosconi, L. Mediterranean diet and 3-year Alzheimer brain biomarker changes in middle-aged adults. Neurology. 2018. 90:e1789–e1798. doi: 10.1212/WNL.0000000000005527 29653991 | Outcome
24 | Beydoun, H. A.,Beydoun, M. A.,Maldonado, A. I.,Fanelli-Kuczmarski, M. T.,Weiss, J.,Evans, M. K.,Zonderman, A. B. Allostatic Load and Cognitive Function Among Urban Adults in the Healthy Aging in Neighborhoods of Diversity across the Life Span Study. J Alzheimers Dis. 2023. 92:425–443. doi: 10.3233/JAD-220888 36776055 | Intervention/Exposure
25 | Bhushan, A.,Fondell, E.,Ascherio, A.,Yuan, C.,Grodstein, F.,Willett, W. Adherence to Mediterranean diet and subjective cognitive function in men. Eur J Epidemiol. 2018. 33:223–234. doi: 10.1007/s10654-017-0330-3 29147948 | Data overlap
26 | Blondal, B. S.,Geirsdottir, O. G.,Halldorsson, T. I.,Beck, A. M.,Jonsson, P. V.,Ramel, A. HOMEFOOD randomised trial - Six-month nutrition therapy improves quality of life, self-rated health, cognitive function, and depression in older adults after hospital discharge. Clin Nutr ESPEN. 2022. 48:74–81. doi: 10.1016/j.clnesp.2022.01.010.35331537 | Intervention/Exposure
27 | Blumenthal, J. A.,Smith, P. J.,Mabe, S.,Hinderliter, A.,Lin, P. H.,Liao, L.,Welsh-Bohmer, K. A.,Browndyke, J. N.,Kraus, W. E.,Doraiswamy, P. M.,Burke, J. R.,Sherwood, A. Lifestyle and neurocognition in older adults with cognitive impairments: A randomized trial. Neurology. 2019. 92:e212–e223. doi: 10.1212/WNL.0000000000006784.30568005 | Participant health status
28 | Blumenthal, J. A.,Smith, P. J.,Mabe, S.,Hinderliter, A.,Welsh-Bohmer, K.,Browndyke, J. N.,Doraiswamy, P. M.,Lin, P. H.,Kraus, W. E.,Burke, J. R.,Sherwood, A. Longer Term Effects of Diet and Exercise on Neurocognition: 1-Year Follow-up of the ENLIGHTEN Trial. J Am Geriatr Soc. 2020. 68:559–568. doi: 10.1111/jgs.16252 31755550 | Participant health status
29 | Bojar, I.,Wierzbińska-Stępniak, A.,Witczak, M.,Raczkiewicz, D.,Owoc, A. Are cognitive functions in post-menopausal women related with the contents of macro- and micro-components in the diet?. Ann Agric Environ Med. 2015. 22:178–84. doi: 10.5604/12321966.1141391 25780851 | Intervention/Exposure
30 | Borda, M.G., Br?nnick, K.K., Garcia-Cifuentes, E., Jaramillo-Jimenez, A., Reyes-Ortiz, C., Patricio-Baldera, J., Soennesyn, H., P?rez-Zepeda, M.U., Vik-Mo, A.O., Aarsland, D.. Specific neuropsychiatric symptoms are associated with functional decline trajectories in Alzheimer?s disease and Lewy body dementia: a five-year follow-up study. Frontiers in Medicine. 2023. 10:1267060. doi: 10.3389/fmed.2023.1267060 37915329 | Intervention/Exposure, Outcome
31 | Bramorska, A.,Zarzycka, W.,Podolecka, W.,Kuc, K.,Brzezicka, A. Age-Related Cognitive Decline May Be Moderated by Frequency of Specific Food Products Consumption. Nutrients. 2021. 13(8):2504. doi: 10.3390/nu13082504 34444664 | Study design
32 | Brinkley, T. E.,Leng, I.,Register, T. C.,Neth, B. J.,Zetterberg, H.,Blennow, K.,Craft, S. Changes in Adiposity and Cerebrospinal Fluid Biomarkers Following a Modified Mediterranean Ketogenic Diet in Older Adults at Risk for Alzheimer’s Disease. Frontiers in Neuroscience. 2022. 16:906539. doi: 10.3389/fnins.2022.906539 35720727 | Study duration 4–8 wk
33 | Cadar, D.,Pikhart, H.,Mishra, G.,Stephen, A.,Kuh, D.,Richards, M. The role of lifestyle behaviors on 20-year cognitive decline. J Aging Res. 2012. 2012:304014. doi: 10.1155/2012/304014 22988508 | Intervention/exposure
34 | Capurso, A.,Solfrizzi, V.,Panza, F.,Torres, F.,Mastroianni, F.,Grassi, A.,Del Parigi, A.,Capurso, C.,Pirozzi, M. R.,Centonze, S.,Misciagna, G. Dietary patterns and cognitive functions in elderly subjects. Aging (Milano). 1997. 9:45–7.9358881 | Publication status
35 | Chan, R.,Chan, D.,Woo, J.. A cross sectional study to examine the association between dietary patterns and cognitive impairment in older Chinese people in Hong Kong. J Nutr Health Aging. 2013. 17:757–65. doi: 10.1007/s12603-013-0348-5 24154648 | Study design, Country
36 | Chan, R.,Yau, F.,Yu, B.,Woo, J.. The Role of Dietary Patterns in the Contribution of Cardiorespiratory Fitness in Community-Dwelling Older Chinese Adults in Hong Kong. J Am Med Dir Assoc. 2019. 20:558–563. doi: 10.1016/j.jamda.2018.12.009 30718152 | Outcome
37 | Charisis, S.,Ntanasi, E.,Yannakoulia, M.,Anastasiou, C. A.,Kosmidis, M. H.,Dardiotis, E.,Gargalionis, A. N.,Patas, K.,Chatzipanagiotou, S.,Mourtzinos, I.,Tzima, K.,Hadjigeorgiou, G.,Sakka, P.,Kapogiannis, D.,Scarmeas, N. Diet Inflammatory Index and Dementia Incidence: A Population-Based Study. Neurology. 2021. 97:e2381–e2391. doi: 10.1212/WNL.0000000000012973 34759053 | Intervention/exposure
38 | Chen, C.,Hayden, K. M.,Kaufman, J. D.,Espeland, M. A.,Whitsel, E. A.,Serre, M. L.,Vizuete, W.,Orchard, T. S.,Wang, X.,Chui, H. C.,D'Alton, M. E.,Chen, J. C.,Kahe, K.. Adherence to a MIND-Like Dietary Pattern, Long-Term Exposure to Fine Particulate Matter Air Pollution, and MRI-Based Measures of Brain Volume: The Women's Health Initiative Memory Study-MRI. Environ Health Perspect. 2021. 129:127008. doi: 10.1289/EHP8036 34939828 | Outcome
39 | Chen, H., Dunk, M.M., Wang, B., Zhao, M., Shen, J., Zong, G., Pan, Y., Tong, L., Xu, W., Yuan, C.. Associations of the Mediterranean-DASH Intervention for Neurodegenerative Delay diet with brain structural markers and their changes. Alzheimer's and Dementia. 2023. 20(2):1190–1200. doi: 10.1002/alz.13521 | Outcome
40 | Chen, R. C.,Chang, Y. H.,Lee, M. S.,Wahlqvist, M. L.. Dietary quality may enhance survival related to cognitive impairment in Taiwanese elderly. Food Nutr Res. 2011. 55. doi: 10.3402/fnr.v55i0.7387 | Study design, Country
41 | Chen, X.,Huang, Y.,Cheng, H. G.. Lower intake of vegetables and legumes associated with cognitive decline among illiterate elderly Chinese: a 3-year cohort study. J Nutr Health Aging. 2012. 16:549–52. doi: 10.1007/s12603-012-0023-2 22659995 | Country
42 | Cherbuin, N.,Anstey, K. J. The Mediterranean diet is not related to cognitive change in a large prospective investigation: the PATH Through Life study. Am J Geriatr Psychiatry. 2012. 20:635–9. doi: 10.1097/JGP.0b013e31823032a9 21937919 | Data overlap
43 | Cherian, L.,Wang, Y.,Fakuda, K.,Leurgans, S.,Aggarwal, N.,Morris, M. Mediterranean-Dash Intervention for Neurodegenerative Delay (MIND) Diet Slows Cognitive Decline After Stroke. J Prev Alzheimers Dis. 2019. 6:267–273. doi: 10.14283/jpad.2019.28 31686099 | Participant health status
44 | Chlebowski, R. T.,Rapp, S.,Aragaki, A. K.,Pan, K.,Neuhouser, M. L.,Snetselaar, L. G.,Manson, J. E.,Wactawski-Wende, J.,Johnson, K. C.,Hayden, K.,Baker, L. D.,Henderson, V. W.,Garcia, L.,Qi, L.,Prentice, R. L.. Low-fat dietary pattern and global cognitive function: Exploratory analyses of the Women's Health Initiative (WHI) randomized Dietary Modification trial. EClinicalMedicine. 2020. 18:100240. doi: 10.1016/j.eclinm.2019.100240 31938786 | Data overlap
45 | Choo, J. M.,Murphy, K. J.,Wade, A. T.,Wang, Y.,Bracci, E. L.,Davis, C. R.,Dyer, K. A.,Woodman, R. J.,Hodgson, J. M.,Rogers, G. B. Interactions between Mediterranean Diet Supplemented with Dairy Foods and the Gut Microbiota Influence Cardiovascular Health in an Australian Population. Nutrients. 2023. 15(16):3645. doi: 10.3390/nu15163645 37630835 | Study duration 8–12 wk
46 | Chou, C. C.,Li, Y. J.,Wang, C. J.,Lyu, L. C.. A mini-flipped, game-based Mediterranean diet learning program on dietary behavior and cognitive function among community-dwelling older adults in Taiwan: A cluster-randomized controlled trial. Geriatr Nurs. 2022. 45:160–168. doi: 10.1016/j.gerinurse.2022.03.009 35489112 | Study duration 8–12 wk
47 | Chuang, S. Y.,Lo, Y. L.,Wu, S. Y.,Wang, P. N.,Pan, W. H. Dietary Patterns and Foods Associated With Cognitive Function in Taiwanese Older Adults: The Cross-sectional and Longitudinal Studies. J Am Med Dir Assoc. 2019. 20:544–550.e4. doi: 10.1016/j.jamda.2018.10.017 30630727 | Country
48 | Corley, J.,Starr, J. M.,McNeill, G.,Deary, I. J.. Do dietary patterns influence cognitive function in old age?. Int Psychogeriatr. 2013. 25:1393–407. doi: 10.1017/S1041610213000793 23732046 | Study design
49 | D Yuan, H Tang, P Yang, C Guo. Taste preferences, cardiometabolic diseases, and mild cognitive impairment: A prospective cohort analysis of older Chinese adults. The British journal of nutrition. 2023. 131(6):1064–1073. doi: 10.1017/S0007114523002593 37935409 | Intervention/exposure
50 | D'Anci, K. E.,Watts, K. L.,Kanarek, R. B.,Taylor, H. A. Low-carbohydrate weight-loss diets. Effects on cognition and mood. Appetite. 2009. 52:96–103. doi: 10.1016/j.appet.2008.08.009 18804129 | Study duration <4 wk, Study design
51 | DE Jensen, KP Ebmeier, T Akbaraly, MG Jansen, A Singh-Manoux, M Kivimäki, E Zsoldos, MC Klein-Flügge, S Suri. The association of longitudinal diet and waist-to-hip ratio from midlife to old age with hippocampus connectivity and memory in old age: a cohort study. bioRxiv: the preprint server for biology. 2023. 12.12.570778. doi: 10.1101/2023.12.12.570778 | Publication status
52 | Dearborn-Tomazos, J. L.,Wu, A.,Steffen, L. M.,Anderson, C. A. M.,Hu, E. A.,Knopman, D.,Mosley, T. H.,Gottesman, R. F.. Association of Dietary Patterns in Midlife and Cognitive Function in Later Life in US Adults Without Dementia. JAMA Netw Open. 2019. 2:e1916641. doi: 10.1001/jamanetworkopen.2019.16641 31800068 | Data overlap
53 | Deschamps, V.,Astier, X.,Ferry, M.,Rainfray, M.,Emeriau, J. P.,Barberger-Gateau, P.. Nutritional status of healthy elderly persons living in Dordogne, France, and relation with mortality and cognitive or functional decline. Eur J Clin Nutr. 2002. 56:305–12. doi: 10.1038/sj.ejcn.1601311 11965506 | Intervention/exposure
54 | Dhana, K.,Evans, D. A.,Rajan, K. B.,Bennett, D. A.,Morris, M. C.. Healthy lifestyle and the risk of Alzheimer dementia: Findings from 2 longitudinal studies. Neurology. 2020. 95:e374–e383. doi: 10.1212/WNL.0000000000009816 32554763 | Intervention/exposure
55 | Dhana, K.,Franco, O. H.,Ritz, E. M.,Ford, C. N.,Desai, P.,Krueger, K. R.,Holland, T. M.,Dhana, A.,Liu, X.,Aggarwal, N. T.,Evans, D. A.,Rajan, K. B.. Healthy lifestyle and life expectancy with and without Alzheimer's dementia: population based cohort study. Bmj. 2022. 377:e068390. doi: 10.1136/bmj-2021-068390 35418416 | Intervention/exposure
56 | Dilmore, A. H.,Martino, C.,Neth, B. J.,West, K. A.,Zemlin, J.,Rahman, G.,Panitchpakdi, M.,Meehan, M. J.,Weldon, K. C.,Blach, C.,Schimmel, L.,Kaddurah-Daouk, R.,Dorrestein, P. C.,Knight, R.,Craft, S.. Effects of a ketogenic and low-fat diet on the human metabolome, microbiome, and foodome in adults at risk for Alzheimer's disease. Alzheimers Dement. 2023. 19:4805–4816. doi: 10.1002/alz.13007 37017243 | Study duration 4–8 wk
57 | Ding, K.,Zeng, J.,Zhang, X.,Wang, Y.,Liang, F.,Wang, L.,Guo, T.,Moore, J. B.,Li, R.. Changes in Plant-Based Dietary Quality and Subsequent Risk of Cognitive Impairment Among Older Chinese Adults: a National Community-Based Cohort Study. Am J Clin Nutr. 2023. 118:201–208. doi: 10.1016/j.ajcnut.2023.05.018 37187294 | Country
58 | Dobreva, I.,Marston, L.,Mukadam, N.. Which components of the Mediterranean diet are associated with dementia? A UK Biobank cohort study. GeroScience. 2022. 44:2541–2554. doi: 10.1007/s11357-022-00615-2 35794436 | Intervention/exposure
59 | Doorduijn, A. S.,de van der Schueren, M. A. E.,van de Rest, O.,de Leeuw, F. A.,Hendriksen, H. M. A.,Teunissen, C. E.,Scheltens, P.,van der Flier, W. M.,Visser, M.. Nutritional Status Is Associated With Clinical Progression in Alzheimer's Disease: The NUDAD Project. J Am Med Dir Assoc. 2023. 24:638–644.e1. doi: 10.1016/j.jamda.2020.10.020 33239240 | Study design
60 | Duan, H.,Zhou, D.,Xu, N.,Yang, T.,Wu, Q.,Wang, Z.,Sun, Y.,Li, Z.,Li, W.,Ma, F.,Chen, Y.,Du, Y.,Zhang, M.,Yan, J.,Sun, C.,Wang, G.,Huang, G.. Association of Unhealthy Lifestyle and Genetic Risk Factors With Mild Cognitive Impairment in Chinese Older Adults. JAMA Netw Open. 2023. 6:e2324031. doi: 10.1001/jamanetworkopen.2023.24031 37462970 | Intervention/exposure
61 | Duggan, M. R.,Butler, L.,Peng, Z.,Daya, G. N.,Moghekar, A.,An, Y.,Rapp, S. R.,Hayden, K. M.,Shadyab, A. H.,Natale, G.,Liu, L.,Snetselaar, L.,Moaddel, R.,Rebholz, C. M.,Sullivan, K.,Ballantyne, C. M.,Resnick, S. M.,Ferrucci, L.,Walker, K. A.. Plasma proteins related to inflammatory diet predict future cognitive impairment. Mol Psychiatry. 2023. 28:1599–1609. doi: 10.1038/s41380-023-01975-7 36737481 | Intervention/exposure
62 | Edwards, L. M.,Murray, A. J.,Holloway, C. J.,Carter, E. E.,Kemp, G. J.,Codreanu, I.,Brooker, H.,Tyler, D. J.,Robbins, P. A.,Clarke, K.. Short-term consumption of a high-fat diet impairs whole-body efficiency and cognitive function in sedentary men. Faseb j. 2011. 25:1088–96. doi: 10.1096/fj.10-171983 21106937 | Study duration, <4 wk
63 | Eskelinen, M. H.,Ngandu, T.,Tuomilehto, J.,Soininen, H.,Kivipelto, M.. Midlife healthy-diet index and late-life dementia and Alzheimer's disease. Dement Geriatr Cogn Dis Extra. 2011. 1:103–12. doi: 10.1159/000327518 22163237 | Data overlap
64 | Estrella, M. L.,Durazo-Arvizu, R. A.,Mattei, J.,Mossavar-Rahmani, Y.,Perreira, K. M.,Siega-Riz, A. M.,Sotres-Alvarez, D.,González, H. M.,Gallo, L. C.,Daviglus, M. L.,Lamar, M.. Alternate Healthy Eating Index is Positively Associated with Cognitive Function Among Middle-Aged and Older Hispanics/Latinos in the HCHS/SOL. J Nutr. 2020. 150:1478–1487. doi: 10.1093/jn/nxaa023 32091597 | Study design
65 | Fan, S. M.,Chiu, P. Y.,Liu, C. H.,Liao, Y. C.,Chang, H. T.. Predictive value of hypercholesterolemia, vegetarian diet, and hypertension for incident dementia among elderly Taiwanese individuals with low educational levels. Ther Adv Chronic Dis. 2023. 14:20406223231171549. doi: 10.1177/20406223231171549 37255548 | Intervention/exposure
66 | Féart, C.,Samieri, C.,Rondeau, V.,Amieva, H.,Portet, F.,Dartigues, J. F.,Scarmeas, N.,Barberger-Gateau, P.. Adherence to a Mediterranean diet, cognitive decline, and risk of dementia. Jama. 2009. 302:638–48. doi: 10.1001/jama.2009.1146 19671905 | Data overlap
67 | Feng, Z.,Cramm, J. M.,Nieboer, A. P.. A healthy diet and physical activity are important to promote healthy ageing among older Chinese people. J Int Med Res. 2019. 47:6061–6081. doi: 10.1177/0300060519882590 31709866 | Study design, Country
68 | Ferrand, C.,Féart, C.,Martinent, G.,Albinet, C.,André, N.,Audiffren, M.. Dietary patterns in French home-living older adults: Results from the PRAUSE study. Arch Gerontol Geriatr. 2017. 70:180–185. doi: 10.1016/j.archger.2017.01.015 28192753 | Study design
69 | Ferreira, N. V.,Lotufo, P. A.,Marchioni, D. M. L.,Barreto, S. M.,Viana, M. C.,Caramelli, P.,Bensenor, I. J. M.,Suemoto, C. K.. Association Between Adherence to the MIND Diet and Cognitive Performance is Affected by Income: The ELSA-Brasil Study. Alzheimer Dis Assoc Disord. 2022. 36:133–139. doi: 10.1097/WAD.0000000000000491 35090161 | Study design
70 | Fieldhouse, J. L. R. Doorduijn, A. S.,de Leeuw, F. A.,Verhaar, B. J. H.,Koene, T.,Wesselman, L. M. P.,Schueren, M. V.,Visser, M.,Rest, O. V.,Scheltens, P.,Kester, M. I.,Flier, W. M. V.. A Suboptimal Diet is Associated with Poorer Cognition: The NUDAD Project. Nutrients. 2020. 12(3);703. doi: 10.3390/nu12030703 32155876 | Study design
71 | Fortune, N. C.,Harville, E. W.,Guralnik, J. M.,Gustat, J.,Chen, W.,Qi, L.,Bazzano, L. A.. Dietary intake and cognitive function: evidence from the Bogalusa Heart Study. Am J Clin Nutr. 2019. 109:1656–1663. doi: 10.1093/ajcn/nqz026 31136655 | Data overlap
72 | Fostinelli, S.,Ferrari, C.,DeAmicis, R.,Giustizieri, V.,Leone, A.,Bertoli, S.,Battezzati, A.,Binetti, G.,Cappa, S. F.. The Impact of Nutrition on Cognitive Performance in a Frail Elderly Population Living in Northern Italy. J Am Nutr Assoc. 2023. 42:484–494. doi: 10.1080/27697061.2022.2084180 35674489 | Study design, Intervention/exposure
73 | Franzon, K.,Byberg, L.,Sjögren, P.,Zethelius, B.,Cederholm, T.,Kilander, L.. Predictors of Independent Aging and Survival: A 16-Year Follow-Up Report in Octogenarian Men. J Am GeriatrSoc. 2017. 65:1953–1960. doi: 10.1111/jgs.14971 | Outcome
74 | Gallucci, M.,Mazzuco, S.,Ongaro, F.,Di Giorgi, E.,Mecocci, P.,Cesari, M.,Albani, D.,Forloni, G. L.,Durante, E.,Gajo, G. B.,Zanardo, A.,Siculi, M.,Caberlotto, L.,Regini, C.. Body mass index, lifestyles, physical performance and cognitive decline: the "Treviso Longeva (TRELONG)" study. J Nutr Health Aging. 2013. 17:378–84. doi: 10.1007/s12603-012-0397-1 23538662 | Intervention/exposure
75 | Gallucci, M.,Pallucca, C.,Di Battista, M. E.,Fougére, B.,Grossi, E.. Artificial Neural Networks Help to Better Understand the Interplay Between Cognition, Mediterranean Diet, and Physical Performance: Clues from TRELONG Study. J Alzheimers Dis. 2019. 71:1321–1330. doi: 10.3233/JAD-190609 31524170 | Study design, Outcome
76 | Gardener, S. L.,Rainey-Smith, S. R.,Barnes, M. B.,Sohrabi, H. R.,Weinborn, M.,Lim, Y. Y.,Harrington, K.,Taddei, K.,Gu, Y.,Rembach, A.,Szoeke, C.,Ellis, K. A..Masters, C. L.,Macaulay, S. L.,Rowe, C. C.,Ames, D.,Keogh, J. B.,Scarmeas, N.,Martins, R. N. Dietary patterns and cognitive decline in an Australian study of ageing. Mol Psychiatry. 2015. 20:860–6. doi: 10.1038/mp.2014.79 25070537 | Data overlap
77 | Gariballa, S.,Forster, S.. Effects of dietary supplements on depressive symptoms in older patients: a randomised double-blind placebo-controlled trial. Clinical nutrition (Edinburgh, Scotland). 2007. 26:545–551. doi: 10.1016/j.clnu.2007.06.007 17662509 | Intervention/exposure, Study duration 4–8 wk
78 | Gatto, N. M.,Garcia-Cano, J.,Irani, C.,Jaceldo-Siegl, K.,Liu, T.,Chen, Z.,Paul, J.,Fraser, G.,Wang, C.,Lee, G. J.. Vegetarian Dietary Patterns and Cognitive Function among Older Adults: The Adventist Health Study-2. J Nutr Gerontol Geriatr. 2021.40:197–214. doi: 10.1080/21551197.2021.1965939 34412570 | Study design
79 | Gauci, S.,Young, L. M.,White, D. J.,Reddan, J. M.,Lassemillante, A. C.,Meyer, D.,Pipingas, A.,Scholey, A. Diet May Moderate the Relationship Between Arterial Stiffness and Cognitive Performance in Older Adults. J Alzheimers Dis. 2022. 85:815–828. doi: 10.3233/JAD-210567 34864661 | Study design
80 | Gaynor, A. M.,Varangis, E.,Song, S.,Gazes, Y.,Habeck, C.,Stern, Y.,Gu, Y. Longitudinal association between changes in resting-state network connectivity and cognition trajectories: The moderation role of a healthy diet. Front Hum Neurosci. 2022. 16:1043423. doi: 10.3233/JAD-210567 36741777 | Intervention/exposure
81 | Gaynor, A. M.,Varangis, E.,Song, S.,Gazes, Y.,Noofoory, D.,Babukutty, R. S.,Habeck, C.,Stern, Y.,Gu, Y.. Diet moderates the effect of resting state functional connectivity on cognitive function. Sci Rep. 2022. 12:16080. doi: 10.1038/s41598-022-20047-4 36167961 | Study design
82 | Gentreau, M.,Chuy, V.,Féart, C.,Samieri, C.,Ritchie, K.,Raymond, M.,Berticat, C.,Artero, S.. Refined carbohydrate-rich diet is associated with long-term risk of dementia and Alzheimer's disease in apolipoprotein E ε4 allele carriers. Alzheimer's and Dementia. 2020. 16:1043–1053. doi: 10.1002/alz.12114 | Intervention/exposure
83 | Gkotzamanis, V.,Panagiotakos, D.,Yannakoulia, M.,Kosmidis, M.,Dardiotis, E.,Hadjigeorgiou, G.,Sakka, P.,Scarmeas, N.. Trajectories of healthy aging and their association with the Mediterranean diet: The HELIAD Study. Maturitas. 2022. 159:33–39. doi: 10.1016/j.maturitas.2022.01.003 35337610 | Outcome
84 | Godos, J.,Grosso, G.,Ferri, R.,Caraci, F.,Lanza, G.,Al-Qahtani, W. H.,Caruso, G.,Castellano, S.. Mediterranean diet, mental health, cognitive status, quality of life, and successful aging in southern Italian older adults. Exp Gerontol. 2023. 175:112143. doi: 10.1016/j.exger.2023.112143 36907474 | Study design
85 | Gopinath, B.,Russell, J.,Kifley, A.,Flood, V. M.,Mitchell, P.. Adherence to Dietary Guidelines and Successful Aging Over 10 Years. J Gerontol A Biol Sci Med Sci. 2016. 71:349–55. doi: 10.1093/gerona/glv189 26503376 | Outcome
86 | Goshen, A., Goldbourt, U., Benyamini, Y., Shimony, T., Keinan-Boker, L., Gerber, Y.. Diet Quality and Incident Frailty in Adults 65 Years or Older: The Israeli Longitudinal Study on Aging. Mayo Clinic Proceedings. 2023. 98:1774. doi: 10.1016/j.mayocp.2023.08.015 38043995 | Publication status, Outcome
87 | Goshen, A.,Goldbourt, U.,Benyamini, Y.,Shimony, T.,Keinan-Boker, L.,Gerber, Y.. Association of Diet Quality With Longevity and Successful Aging in Israeli Adults 65 Years or Older. JAMA Netw Open. 2022. 5:e2214916. doi: 10.1001/jamanetworkopen.2022.14916 35648399 | No key confounders accounted for
88 | Gu, Q.,Sable, C. M.,Brooks-Wilson, A.,Murphy, R. A.. Dietary patterns in the healthy oldest old in the healthy aging study and the Canadian longitudinal study of aging: a cohort study. BMC Geriatr. 2020. 20:106. doi: 10.1186/s12877-020-01507-w 32178631 | Outcome
89 | Gu, Y.,Guo, J.,Moshfegh, A. J.. Race/ethnicity and gender modify the association between diet and cognition in U.S. older adults: National Health and Nutrition Examination Survey 2011–2014. Alzheimer's and Dementia: Translational Research and Clinical Interventions. 2021. 7(1);e12128. doi: 10.1002/trc2.12128 | Study design
90 | Gu, Y.,Luchsinger, J. A.,Stern, Y.,Scarmeas, N.. Mediterranean diet, inflammatory and metabolic biomarkers, and risk of Alzheimer's disease. J Alzheimers Dis. 2010. 22:483–92. doi: 10.3233/JAD-2010-100897 20847399 | Data overlap
91 | Guan, Y., Cheng, C.H., Bellomo, L.I., Narain, S., Bigornia, S.J., Garelnabi, M.O., Scott, T., Ordov?s, J.M., Tucker, K.L., Bhadelia, R., Koo, B.-B.. APOE4 allele-specific associations between diet, multimodal biomarkers, and cognition among Puerto Rican adults in Massachusetts. Frontiers in Aging Neuroscience. 2023. 15:15:1285333. doi: 10.3389/fnagi.2023.1285333 38035273 | Intervention/exposure
92 | Gyorkos, A.,Baker, M. H.,Miutz, L. N.,Lown, D. A.,Jones, M. A.,Houghton-Rahrig, L. D.. Carbohydrate-restricted Diet and Exercise Increase Brain-derived Neurotrophic Factor and Cognitive Function: A Randomized Crossover Trial. Cureus. 2019. 11:e5604. doi: 10.7759/cureus.5604 31700717 | Study duration <4 wk
93 | Halloway, S.,Wagner, M.,Tangney, C.,Lange-Maia, B. S.,Bennett, D. A.,Arvanitakis, Z.,Schoeny, M. E.. Profiles of lifestyle health behaviors and cognitive decline in older adults. Alzheimers Dement. 2023. 20(1):472–482. doi: 10.1002/alz.13459 37676928 | Intervention/exposure
94 | Halyburton, A. K.,Brinkworth, G. D.,Wilson, C. J.,Noakes, M.,Buckley, J. D.,Keogh, J. B.,Clifton, P. M.. Low- and high-carbohydrate weight-loss diets have similar effects on mood but not cognitive performance. Am J Clin Nutr. 2007. 86:580–7. doi: 10.1093/ajcn/86.3.580 17823420 | Study duration 8–12 wk, Intervention/exposure
95 | Hardman, R. J.,Meyer, D.,Kennedy, G.,Macpherson, H.,Scholey, A. B.,Pipingas, A.. Findings of a Pilot Study Investigating the Effects of Mediterranean Diet and Aerobic Exercise on Cognition in Cognitively Healthy Older People Living Independently within Aged-Care Facilities: The Lifestyle Intervention in Independent Living Aged Care (LIILAC) Study. Curr Dev Nutr. 2020. 4:nzaa077. doi: 10.1093/cdn/nzaa077 32440639 | Size of study groups
96 | Hardman, R. J.,Meyer, D.,Kennedy, G.,Macpherson, H.,Scholey, A. B.,Pipingas, A.. The association between adherence to a Mediterranean style diet and cognition in older people: The impact of medication. Clin Nutr. 2018. 37:2156–2165. doi: 10.1016/j.clnu.2017.10.015 29217146 | Study design
97 | Haring, B.,Wu, C.,Mossavar-Rahmani, Y.,Snetselaar, L.,Brunner, R.,Wallace, R. B.,Neuhouser, M. L.,Wassertheil-Smoller, S.. No Association between Dietary Patterns and Risk for Cognitive Decline in Older Women with 9-Year Follow-Up: Data from the Women's Health Initiative Memory Study. J Acad Nutr Diet. 2016. 116:921–930.e1. doi: 10.1016/j.jand.2015.12.017 27050728 | Data overlap
98 | Harris, E.. MIND Diet No Better Than Control for Adults at Risk of Dementia. Jama. 2023. 330:585. doi: 10.1001/jama.2023.13134 | Publication status
99 | Hassan, S.,Aguirre, E.,Betz, A.,Robertson, S.,Sankhla, D.,Cooper, C.. Evaluating the effect of Brainfood groups for people with mild cognitive impairment and mild dementia: preliminary mixed-methodology study. BJPsych Open. 2018. 4:208–214. doi: 10.1192/bjo.2018.29 29988927 | Study design, study duration 4–8 wk
100 | Hayden, K. M.,Beavers, D. P.,Steck, S. E.,Hebert, J. R.,Tabung, F. K.,Shivappa, N.,Casanova, R.,Manson, J. E.,Padula, C. B.,Salmoirago-Blotcher, E.,Snetselaar, L. G.,Zaslavsky, O.,Rapp, S. R.. The association between an inflammatory diet and global cognitive function and incident dementia in older women: The Women's Health Initiative Memory Study. Alzheimer's and Dementia. 2017. 13:1187–1196. doi: 10.1016/j.jalz.2017.04.004 | Intervention/exposure
101 | Holloway, C. J.,Cochlin, L. E.,Emmanuel, Y.,Murray, A.,Codreanu, I.,Edwards, L. M.,Szmigielski, C.,Tyler, D. J.,Knight, N. S.,Saxby, B. K.,Lambert, B.,Thompson, C.,Neubauer, S.,Clarke, K.. A high-fat diet impairs cardiac high-energy phosphate metabolism and cognitive function in healthy human subjects. Am J Clin Nutr. 2011. 93:748–55. doi: 10.3945/ajcn.110.002758 21270386 | Study duration <4 wk
102 | Hoscheidt, S.,Sanderlin, A. H.,Baker, L. D.,Jung, Y.,Lockhart, S.,Kellar, D.,Whitlow, C. T.,Hanson, A. J.,Friedman, S.,Register, T.,Leverenz, J. B.,Craft, S.. Mediterranean and Western diet effects on Alzheimer's disease biomarkers, cerebral perfusion, and cognition in mid-life: A randomized trial. Alzheimers Dement. 2022. 18:457–468. doi: 10.1002/alz.12421 34310044 | Study duration <4 wk
103 | Hosking, D. E.,Nettelbeck, T.,Wilson, C.,Danthiir, V.. Retrospective lifetime dietary patterns predict cognitive performance in community-dwelling older Australians. Br J Nutr. 2014. 112:228–37. doi: 10.1017/S0007114514000646 24709049 | Study design
104 | Hossain, S.,Beydoun, M. A.,Weiss, J.,Kuczmarski, M. F.,Evans, M. K.,Zonderman, A. B.. Longitudinal associations between dietary quality and Alzheimer's disease genetic risk on cognitive performance among African American adults. Br J Nutr. 2020. 124:1264–1276. doi: 10.1017/S0007114520001269 32248879 | Intervention/exposure
105 | Hou, C.,Lin, Y.,Zimmer, Z.,Fang, X.. The association of healthy behaviors with cognitive health expectancy in Chinese older adults: a population-based cohort study. Aging (Albany NY). 2020. 12:16999–17021. doi: 10.18632/aging.103617 32903212 | Intervention/exposure
106 | Hu, W.,Zhang, H.,Ni, R.,Cao, Y.,Fang, W.,Chen, Y.,Pan, G.. Interaction between the animalbased dietary pattern and green space on cognitive function among Chinese older adults: A prospective cohort study. Int J Hyg Environ Health. 2023. 250:114147. doi: 10.1016/j.ijheh.2023.114147 36893615 | Country
107 | Huang, L.,Tao, Y.,Chen, H.,Chen, X.,Shen, J.,Zhao, C.,Xu, X.,He, M.,Zhu, D.,Zhang, R.,Yang, M.,Zheng, Y.,Yuan, C.. Mediterranean-Dietary Approaches to Stop Hypertension Intervention for Neurodegenerative Delay (MIND) Diet and Cognitive Function and its Decline: A Prospective Study and Meta-analysis of Cohort Studies. American Journal of Clinical Nutrition. 2023. 118:174–182. doi: 10.1016/j.ajcnut.2023.04.025 37105521 | Country
108 | Huang, Q.,Jiang, H.,Zhang, J.,Jia, X.,Huang, F.,Wang, H.,Zhang, B.,Wang, L.,Gu, M.,Huang, Y.,Shi, W.,Ma, Y.,Zhang, X.,Wang, Z.. Dietary Patterns Are Associated With MultiDimensional Cognitive Functions Among Adults Aged 55 and Older in China. Front Nutr. 2022. 9:806871. doi: 10.3389/fnut.2022.806871 35252296 | Study design
109 | I Domínguez-López, R Casas, G Chiva-Blanch, MÁ Martínez-González, M Fitó, E Ros, RM Lamuela-Raventós, R Estruch. Serum vitamin B12 concentration is associated with improved memory in older individuals with higher adherence to the Mediterranean diet. Clinical nutrition (Edinburgh, Scotland). 2023. 42(12):2562–2568. doi: 10.1016/j.clnu.2023.10.025 37948836 | Intervention/exposure
110 | Jakobsen, L. H.,Kondrup, J.,Zellner, M.,Tetens, I.,Roth, E. Effect of a high protein meat diet on muscle and cognitive functions: A randomised controlled dietary intervention trial in healthy men. Clinical Nutrition. 2011. 30:303–311. doi: 10.1016/j.clnu.2010.12.010 21239090 | Study duration <4 wk
111 | Jeong EH., E Kim, CH Hong, SY Moon, HK Park, JH Jeong, HR Na, SH Choi, YK Park. Practicability of Six Weeks of Korean-Style Mediterranean Diet for Elderly Koreans with High Risk for Dementia. J korean diet assoc. 2019. 25:237–256. | Study duration 4-8 wk
112 | Jia, F.,Liu, F.,Li, X.,Shi, X.,Liu, Y.,Cao, F. Cognitive reserve, modifiable-risk-factor profile and incidence of dementia: results from a longitudinal study of CFAS Wales. Aging Ment Health. 2021. 25:2286–2292. doi: 10.1080/13607863.2020.1828270 33021096 | Intervention/exposure
113 | Jia, J.,Zhao, T.,Liu, Z.,Liang, Y.,Li, F.,Li, Y.,Liu, W.,Li, F.,Shi, S.,Zhou, C.,Yang, H.,Liao, Z.,Li, Y.,Zhao, H.,Zhang, J.,Zhang, K.,Kan, M.,Yang, S.,Li, H.,Liu, Z.,Ma, R.,Lv, J.,Wang, Y.,Yan, X.,Liang, F.,Yuan, X.,Zhang, J..Gauthier, S.,Cummings, J.. Association between healthy lifestyle and memory decline in older adults: 10 year, population based, prospective cohort study. Bmj. 2023. 380:e072691. doi: 10.1136/bmj-2022-072691 36696990 | Intervention/exposure
114 | Kackley, M. L.,Brownlow, M. L.,Buga, A..Crabtree, C. D..Sapper, T. N.,O'Connor, A.,Volek, J. S.. The effects of a 6-week controlled, hypocaloric ketogenic diet, with and without exogenous ketone salts, on cognitive performance and mood states in overweight and obese adults. Front Neurosci. 2022. 16:971144. doi: 10.3389/fnins.2022.971144 36248655 | Study duration 4–8 wk
115 | Kaplan, A.,Zelicha, H.,Yaskolka Meir, A.,Rinott, E.,Tsaban, G.,Levakov, G.,Prager, 0.,Salti, M.,Yovell, Y.,Ofer, J.,Huhn, S.,Beyer, F.,Witte, V.,Villringer, A.,Meiran, N.,Emesh, T. B.,Kovacs, P.,Von Bergen, M.,Ceglarek, U.,Blüher, M.,Stumvoll, M.,Hu, F. B.,Stampfer, M. J..Friedman, A.,Shelef, I.,Avidan, G.,Shai, I.. The effect of a high-polyphenol Mediterranean diet (Green-MED) combined with physical activity on age-related brain atrophy: the Dietary Intervention Randomized Controlled Trial Polyphenols Unprocessed Study (DIRECT PLUS). American Journal of Clinical Nutrition. 2022. 115:1270–1281. doi: 10.1093/ajcn/nqac001 35021194 | Outcome
116 | Katsiardanis, K.,Diamantaras, A. A.,Dessypris, N.,Michelakos, T.,Anastasiou, A.,Katsiardani, K. P.,Kanavidis, P.,Papadopoulos, F. C.,Stefanadis, C.,Panagiotakos, D. B.,Petridou, E. T.. Cognitive impairment and dietary habits among elders: the Velestino Study. J Med Food. 2013. 16:343–50. doi: 10.1089/jmf.2012.0225 23514229 | Study design
117 | Kesse-Guyot, E.,Amieva, H.,Castetbon, K.,Henegar, A.,Ferry, M.,Jeandel, C.,Hercberg, S.,Galan, P.. Adherence to nutritional recommendations and subsequent cognitive performance: findings from the prospective Supplementation with Antioxidant Vitamins and Minerals 2 (SU.VI.MAX 2) study. American journal of clinical nutrition. 2011.93:200–210. doi: 10.3945/ajcn.2010.29761 21106918 | Data overlap
118 | Kesse-Guyot, E.,Andreeva, V. A.,Ducros, V.,Jeandel, C.,Julia, C.,Hercberg, S.,Galan, P.. Carotenoid-rich dietary patterns during midlife and subsequent cognitive function. Br J Nutr. 2014. 111:915–23. doi: 10.1017/S0007114513003188 24073964 | Data overlap
119 | Kesse-Guyot, E.,Andreeva, V. A.,Jeandel, C.,Ferry, M.,Hercberg, S.,Galan, P. A healthy dietary pattern at midlife is associated with subsequent cognitive performance. J Nutr. 2012. 142:909–15. doi: 10.3945/jn.111.156257 22457391 | Data overlap
120 | Kesse-Guyot, E.,Andreeva, V. A.,Lassale, C.,Ferry, M.,Jeandel, C.,Hercberg, S.,Galan, P. Mediterranean diet and cognitive function: a French study. Am J Clin Nutr. 2013. 97:369–76. doi: 10.3945/ajcn.112.047993 23283500 | Data overlap
121 | Kesse-Guyot, E.,Assmann, K. E.,Andreeva, V. A.,Touvier, M.,Neufcourt, L.,Shivappa, N.,Hébert, J. R.,Wirth, M. D.,Hercberg, S.,Galan, P.,Julia, C. Long-term association between the dietary inflammatory index and cognitive functioning: findings from the SU.VI.MAX study. Eur J Nutr. 2017. 56:1647–1655. doi: 10.1007/s00394-016-1211-3 27055851 | Intervention/exposure
122 | Kim, K. Y.,Yun, J. M. Association between diets and mild cognitive impairment in adults aged 50 years or older. Nutr Res Pract. 2018. 12:415–425. doi: 10.4162/nrp.2018.12.5.415 30323909 | Study design
123 | Klinedinst, B. S.,Le, S. T.,Larsen, B.,Pappas, C.,Hoth, N. J.,Pollpeter, A.,Wang, Q.,Wang, Y.,Yu, S.,Wang, L.,Allenspach, K.,Mochel, J. P.,Bennett, D. A.,Willette, A. A. Genetic Factors of Alzheimer's Disease Modulate How Diet is Associated with Long-Term Cognitive Trajectories: A UK Biobank Study. J Alzheimers Dis. 2020. 78:1245–1257. doi: 10.3233/JAD-201058 33252089 | Intervention/exposure
124 | Knight, A.,Bryan, J.,Wilson, C.,Hodgson, J. M.,Davis, C. R.,Murphy, K. J. The Mediterranean Diet and Cognitive Function among Healthy Older Adults in a 6-Month Randomised Controlled Trial: The MedLey Study. Nutrients. 2016. 8(9):579. doi: 10.3390/nu8090579 27657119 | Data overlap
125 | Knight, A.,Bryan, J.,Wilson, C.,Hodgson, J.,Murphy, K. A randomised controlled intervention trial evaluating the efficacy of a Mediterranean dietary pattern on cognitive function and psychological wellbeing in healthy older adults: the MedLey study. BMC Geriatr. 2015. 15:55. doi: 10.1186/s12877-015-0054-8 25928696 | Study design, Publication status
126 | Koblinsky, N. D.,Anderson, N. D.,Ajwani, F.,Parrott, M. D.,Dawson, D.,Marzolini, S.,Oh, P.,MacIntosh, B.,Middleton, L.,Ferland, G.,Greenwood, C. E. Feasibility and preliminary efficacy of the LEAD trial: a cluster randomized controlled lifestyle intervention to improve hippocampal volume in older adults at-risk for dementia. Pilot Feasibility Stud. 2022. 8:37. doi: 10.1186/s40814-022-00977-6 35139918 | Size of study groups
127 | Koyama, A.,Houston, D. K.,Simonsick, E. M.,Lee, J. S.,Ayonayon, H. N.,Shahar, D. R.,Rosano, C.,Satterfield, S.,Yaffe, K. Association between the Mediterranean diet and cognitive decline in a biracial population. J Gerontol A Biol Sci Med Sci. 2015. 70:354–9. doi: 10.1093/gerona/glu097 24994847 | Data overlap
128 | Kühn, L.,MacIntyre, U. E.,Kotzé, C.,Becker, P. J.,Wenhold, F. A. M. Twelve Weeks of Additional Fish Intake Improves the Cognition of Cognitively Intact, Resource-Limited Elderly People: A Randomized Control Trial. Journal of Nutrition, Health and Aging. 2022. 26:119–126. doi: 10.1007/s12603-021-1723-2 | Size of study groups
129 | Kwok, T. C.,Lam, L. C.,Sea, M. M.,Goggins, W.,Woo, J. A randomized controlled trial of dietetic interventions to prevent cognitive decline in old age hostel residents. Eur J Clin Nutr. 2012. 66:1135–40. doi: 10.1038/ejcn.2012.117 22948946 | Intervention/exposure, Country
130 | L Huang, H Chen, M Gao, J Shen, Y Tao, Y Huang, R Lv, R Xie, X Lv, X Xu, X Xu, C Yuan. Dietary factors in relation to the risk of cognitive impairment and physical frailty in Chinese older adults: a prospective cohort study. European journal of nutrition. 2023. 63(1):267–277. doi: 10.1007/s00394-023-03260-3 37930363 | Country
131 | Lee, A. T. C.,Richards, M.,Chan, W. C.,Chiu, H. F. K.,Lee, R. S. Y.,Lam, L. C. W. Lower risk of incident dementia among Chinese older adults having three servings of vegetables and two servings of fruits a day. Age Ageing. 2017. 46:773–779. doi: 10.1093/ageing/afx018 28338708 | Intervention/exposure
132 | Lee, J.,Pase, M.,Pipingas, A.,Raubenheimer, J.,Thurgood, M.,Villalon, L.,Macpherson, H.,Gibbs, A.,Scholey, A. Switching to a 10-day Mediterranean-style diet improves mood and cardiovascular function in a controlled crossover study. Nutrition. 2015. 31:647–52. doi:25837207 | Study duration <4 wk
133 | Lehtisalo, J.,Levälahti, E.,Lindström, J.,Hänninen, T.,Paajanen, T.,Peltonen, M.,Antikainen, R.,Laatikainen, T.,Strandberg, T.,Soininen, H.,Tuomilehto, J.,Kivipelto, M.,Ngandu, T.. Dietary changes and cognition over 2 years within a multidomain intervention trial-The Finnish Geriatric Intervention Study to Prevent Cognitive Impairment and Disability (FINGER). Alzheimers Dement. 2019. 15:410–417. doi: 10.1093/ageing/afx018 30527596 | Intervention/exposure
134 | Lehtisalo, J.,Ngandu, T.,Valve, P.,Antikainen, R.,Laatikainen, T.,Strandberg, T.,Soininen, H.,Tuomilehto, J.,Kivipelto, M.,Lindström, J. Nutrient intake and dietary changes during a 2-year multi-domain lifestyle intervention among older adults: secondary analysis of the Finnish Geriatric Intervention Study to Prevent Cognitive Impairment and Disability (FINGER) randomised controlled trial. Br J Nutr. 2017. 118:291–302. doi: 10.1017/S0007114517001982 28875868 | Intervention/exposure
135 | Leidy, H. J.,Todd, C. B.,Zino, A. Z.,Immel, J. E.,Mukherjea, R.,Shafer, R. S.,Ortinau, L. C.,Braun, M. Consuming High-Protein Soy Snacks Affects Appetite Control, Satiety, and Diet Quality in Young People and Influences Select Aspects of Mood and Cognition. J Nutr. 2015. 145:1614–22. doi: 10.3945/jn.115.212092 25995282 | Study duration <4 wk
136 | Li, J.,Capuano, A. W.,Agarwal, P.,Arvanitakis, Z.,Wang, Y.,De Jager, P. L.,Schneider, J. A.,Tasaki, S.,de Paiva Lopes, K.,Hu, F. B.,Bennett, D. A.,Liang, L.,Grodstein, F. The MIND diet, brain transcriptomic alterations, and dementia. medRxiv. 2023. Preprint. doi: 10.1101/2023.06.12.23291263 | Publication status
137 | Li, J.,Ogrodnik, M.,Kolachalama, V. B.,Lin, H.,Au, R. Assessment of the Mid-Life Demographic and Lifestyle Risk Factors of Dementia Using Data from the Framingham Heart Study Offspring Cohort. Journal of Alzheimer's Disease. 2018. 63:1119–1127. doi: 10.3233/JAD-170917 | Intervention/exposure, Data overlap
138 | Liebson, P. R. Diet, lifestyle, and hypertension and mediterranean diet and risk of dementia. Preventive Cardiology. 2010. 13:94–96. doi: 10.1111/j.1751-7141.2009.00064.x 20377813 | Study design, Data overlap
139 | Liu, D.,Zhang, W. T.,Wang, J. H.,Shen, D.,Zhang, P. D.,Li, Z. H.,Chen, P. L.,Zhang, X. R.,Huang, Q. M.,Zhong, W. F.,Shi, X. M.,Mao, C. Association between Dietary Diversity Changes and Cognitive Impairment among Older People: Findings from a Nationwide Cohort Study. Nutrients. 2022. 14(6):1251. doi: 10.3390/nu14061251 35334911 | Country
140 | Liu, X.,Morris, M. C.,Dhana, K.,Ventrelle, J.,Johnson, K.,Bishop, L.,Hollings, C. S.,Boulin, A.,Laranjo, N.,Stubbs, B. J.,Reilly, X.,Carey, V. J.,Wang, Y.,Furtado, J. D.,Marcovina, S. M.,Tangney, C.,Aggarwal, N. T.,Arfanakis, K.,Sacks, F. M.,Barnes, L. L. Mediterranean-DASH Intervention for Neurodegenerative Delay (MIND) study: Rationale, design and baseline characteristics of a randomized control trial of the MIND diet on cognitive decline. Contemp Clin Trials. 2021. 102:106270. doi: 10.1016/j.cct.2021.106270 33434704 | Publication Status
141 | Lourida, I.,Hannon, E.,Littlejohns, T. J.,Langa, K. M.,Hyppönen, E.,Kuzma, E.,Llewellyn, D. J. Association of Lifestyle and Genetic Risk With Incidence of Dementia. Jama. 2019. 322:430–437. doi: 10.1001/jama.2019.9879 31302669 | Intervention/exposure
142 | Lu, Y.,Gwee, X.,Chua, D. Q.,Lee, T. S.,Lim, W. S.,Chong, M. S.,Yap, P.,Yap, K. B.,Rawtaer, I.,Liew, T. M.,Pan, F.,Ng, T. P. Nutritional Status and Risks of Cognitive Decline and Incident Neurocognitive Disorders: Singapore Longitudinal Ageing Studies. J Nutr Health Aging. 2021. 25:660–667. doi: 10.1007/s12603-021-1603-9 33949634 | Intervention/exposure
143 | M McMaster, S Kim, L Clare, SJ Torres, N Cherbuin, KJ Anstey. The feasibility of a multidomain dementia risk reduction randomised controlled trial for people experiencing cognitive decline: the Body, Brain, Life for Cognitive Decline (BBL-CD). Aging & mental health. 2023. 27(11):2111–2119. doi: 10.1080/13607863.2023.2190083 36995254 | Study duration 8–12 wk
144 | Mahmoudzadeh, S., Mohammadifard, M., Khorasanchi, Z., Karbasi, S., Ferns, G.A., Bahrami, A. Adherence to a Mediterranean diet style and psychological distress and quality of life in young women. Psychiatria. 2023. 20:89. doi: 10.5603/PSYCH.a2023.0013 | Study design
145 | Mamalaki, E.,Charisis, S.,Anastasiou, C. A.,Ntanasi, E.,Georgiadi, K.,Balomenos, V.,Kosmidis, M. H.,Dardiotis, E.,Hadjigeorgiou, G.,Sakka, P.,Scarmeas, N.,Yannakoulia, M. The Longitudinal Association of Lifestyle with Cognitive Health and Dementia Risk: Findings from the HELIAD Study. Nutrients. 2022. 14(14):2818. doi: 10.3390/nu14142818 35889774 | Data overlap
146 | Mamalaki, E.,Ntanasi, E.,Hatzimanolis, A.,Basta, M.,Kosmidis, M. H.,Dardiotis, E.,Hadjigeorgiou, G. M.,Sakka, P.,Scarmeas, N.,Yannakoulia, M. The Association of Adherence to the Mediterranean Diet with Depression in Older Adults Longitudinally Taking into Account Cognitive Status: Results from the HELIAD Study. Nutrients. 2023. 15(2):359. doi: 10.3390/nu15020359 36678230 | Outcome
147 | Männikkö, R.,Komulainen, P.,Schwab, U.,Heikkilä, H. M.,Savonen, K.,Hassinen, M.,Hänninen, T.,Kivipelto, M.,Rauramaa, R. The Nordic diet and cognition--The DR's EXTRA Study. Br J Nutr. 2015. 114:231–9. doi: 10.1017/S0007114515001890 26104270 | Data overlap
148 | Mantzorou, M.,Vadikolias, K.,Pavlidou, E.,Tryfonos, C.,Vasios, G.,Serdari, A.,Giaginis, C. Mediterranean diet adherence is associated with better cognitive status and less depressive symptoms in a Greek elderly population. Aging Clin Exp Res. 2021. 33:1033–1040. doi: 10.1007/s40520-020-01608-x 32488472 | Study design
149 | Marcason, W. What Are the Components to the MIND Diet? J Acad Nutr Diet. 2015. 115:1744. doi: 10.1016/j.jand.2015.08.002 26407649 | Study design
150 | Margara-Escudero, H. J.,Zamora-Ros, R.,de Villasante, I.,Crous-Bou, M.,Chirlaque, M. D.,Amiano, P.,Mar, J.,Barricarte, A.,Ardanaz, E.,Huerta, J. M. Association Between Egg Consumption and Dementia Risk in the EPIC-Spain Dementia Cohort. Front Nutr. 2022. 9:827307. doi: 10.3389/fnut.2022.827307 35284440 | Intervention/exposure
151 | Marseglia, A.,Xu, W.,Fratiglioni, L.,Fabbri, C.,Berendsen, A. A. M.,Bialecka-Debek, A.,Jennings, A.,Gillings, R.,Meunier, N.,Caumon, E.,Fairweather-Tait, S.,Pietruszka, B.,De Groot, Lcpgm,Santoro, A.,Franceschi, C. Effect of the NU-AGE Diet on Cognitive Functioning in Older Adults: A Randomized Controlled Trial. Front Physiol. 2018. 9:349. doi: 10.3389/fphys.2018.00349 29670545 | Data overlap
152 | Martínez-Lapiscina, E. H.,Clavero, P.,Toledo, E.,Estruch, R.,Salas-Salvadó, J.,San Julián, B.,Sanchez-Tainta, A.,Ros, E.,Valls-Pedret, C.,Martinez-Gonzalez, MÁ. Mediterranean diet improves cognition: the PREDIMED-NAVARRA randomised trial. J Neurol Neurosurg Psychiatry. 2013. 84:1318–25. doi: 10.1136/jnnp-2012-304792 23670794 | Data overlap
153 | Martínez-Lapiscina, E. H.,Clavero, P.,Toledo, E.,San Julián, B.,Sanchez-Tainta, A.,Corella, D.,Lamuela-Raventós, R. M.,Martínez, J. A.,Martínez-Gonzalez, MÁ. Virgin olive oil supplementation and long-term cognition: the PREDIMED-NAVARRA randomized, trial. J Nutr Health Aging. 2013. 17:544–52. doi: 10.1007/s12603-013-0027-6 23732551 | Data overlap
154 | Martínez-Lapiscina, E. H.,Galbete, C.,Corella, D.,Toledo, E.,Buil-Cosiales, P.,Salas-Salvado, J.,Ros, E.,Martinez-Gonzalez, M. A. Genotype patterns at CLU, CR1, PICALM and APOE, cognition and Mediterranean diet: the PREDIMED-NAVARRA trial. Genes Nutr. 2014. 9:393. doi: 10.1007/s12263-014-0393-7 24643340 | Intervention/exposure
155 | Matthews, D. C.,Davies, M.,Murray, J.,Williams, S.,Tsui, W. H.,Li, Y.,Andrews, R. D.,Lukic, A.,McHugh, P.,Vallabhajosula, S.,de Leon, M. J.,Mosconi, L. Physical Activity, Mediterranean Diet and Biomarkers-Assessed Risk of Alzheimer's: A Multi-Modality Brain Imaging Study. Adv J Mol Imaging. 2014. 4:43–57. doi: 10.4236/ami.2014.44006 25599008 | Study design, Outcome
156 | Mazza, E.,Fava, A.,Ferro, Y.,Moraca, M.,Rotundo, S.,Colica, C.,Provenzano, F.,Terracciano, R.,Greco, M.,Foti, D.,Gulletta, E.,Russo, D.,Bosco, D.,Pujia, A.,Montalcini, T. Impact of legumes and plant proteins consumption on cognitive performances in the elderly. J Transl Med. 2017. 15:109. doi: 10.1186/s12967-017-1209-5 28532453 | Intervention/exposure
157 | Mazza, E.,Fava, A.,Ferro, Y.,Rotundo, S.,Romeo, S.,Bosco, D.,Pujia, A.,Montalcini, T. Effect of the replacement of dietary vegetable oils with a low dose of extra virgin olive oil in the Mediterranean Diet on cognitive functions in the elderly. J Transl Med. 2018. 16:10. doi: 10.1186/s12967-018-1386-x 29351799 | Intervention/exposure
158 | McEvoy, C. T.,Hoang, T.,Sidney, S.,Steffen, L. M.,Jacobs, D. R., Jr.,Shikany, J. M.,Wilkins, J. T.,Yaffe, K. Dietary patterns during adulthood and cognitive performance in midlife: The CARDIA study. Neurology. 2019. 92:e1589–e1599. doi: 10.1212/WNL.0000000000007243 30842290 | Data overlap
159 | McLeod, A.,Bernabe, B. P.,Xia, Y.,Sanchez-Flack, J.,Lamar, M.,Schiffer, L.,Hemphill, N. O.,Fantuzzi, G.,Maki, P.,Fitzgibbon, M.,Tussing-Humphreys, L. Exploring the Effects of a Mediterranean Diet and Weight Loss on the Gut Microbiome and Cognitive Performance in Older, African American Obese Adults: A Post Hoc Analysis. Nutrients. 2023. 15(15):3322. doi: 10.3390/nu15153332 37571259 | Intervention/exposure
160 | McMaster, M.,Kim, S.,Clare, L.,Torres, S. J.,Cherbuin, N.,DʼEste, C.,Anstey, K. J. Lifestyle Risk Factors and Cognitive Outcomes from the Multidomain Dementia Risk Reduction Randomized Controlled Trial, Body Brain Life for Cognitive Decline (BBL-CD). J Am Geriatr Soc. 2020. 68:2629–2637. doi: 10.1111/jgs.16762 32909259 | Study duration 8–12 wk
161 | McMillan, L.,Owen, L.,Kras, M.,Scholey, A. Behavioural effects of a 10-day Mediterranean diet. Results from a pilot study evaluating mood and cognitive performance. Appetite. 2011. 56:143–7. doi: 10.1016/j.appet.2010.11.149 21115083 | Study duration <4 wk
162 | Morris, M. C.,Tangney, C. C.,Wang, Y.,Sacks, F. M.,Bennett, D. A.,Aggarwal, N. T. MIND diet associated with reduced incidence of Alzheimer's disease. Alzheimers Dement. 2015. 11:1007–14. doi: 10.1016/j.jalz.2014.11.009 25681666 | Data overlap
163 | Nagpal, R.,Neth, B. J.,Wang, S.,Craft, S.,Yadav, H. Modified Mediterranean-ketogenic diet modulates gut microbiome and short-chain fatty acids in association with Alzheimer's disease markers in subjects with mild cognitive impairment. EBioMedicine. 2019. 47:529–542. doi: 10.1016/j.ebiom.2019.08.032 31477562 | Study duration 4–8 wk
164 | Nagpal, R.,Neth, B. J.,Wang, S.,Mishra, S. P.,Craft, S.,Yadav, H. Gut mycobiome and its interaction with diet, gut bacteria and alzheimer's disease markers in subjects with mild cognitive impairment: A pilot study. EBioMedicine. 2020. 59:102950. doi: 10.1016/j.ebiom.2020.102950 32861197 | Study duration 4–8 wk
165 | Nicolas, A. S.,Faisant, C.,Nourhashemi, F.,Lanzmann-Petithory, D.,Vellas, B. Associations between nutritional intake and cognitive function in a healthy ageing sample: A 4-year reassessment. European Journal of Geriatrics. 2000. 2:114–119. | Data overlap
166 | Nicole, W. Food for Thought: Exploring the Relationship between PM2:5 Exposure, Dietary Patterns, and Changes in Brain Volume. Environmental Health Perspectives. 2022. 130(4):044001. doi: 10.1289/EHP11017 35377218 | Publication status
167 | Nilsson, A.,Tovar, J.,Johansson, M.,Radeborg, K.,Björck, I. A diet based on multiple functional concepts improves cognitive performance in healthy subjects. Nutr Metab (Lond). 2013. 10:49. doi: 10.1186/1743-7075-10-49 23855966 | Study duration <4 wk
168 | Nooyens, A. C.,Bueno-de-Mesquita, H. B.,van Boxtel, M. P.,van Gelder, B. M.,Verhagen, H.,Verschuren, W. M. Fruit and vegetable intake and cognitive decline in middle-aged men and women: the Doetinchem Cohort Study. Br J Nutr. 2011. 106:752–61. doi: 10.1017/S0007114511001024 21477405 | Study design
169 | Ntanasi, E.,Charisis, S.,Yannakoulia, M.,Georgiadi, K.,Balomenos, V.,Kosmidis, M. H.,Dardiotis, Ε,Hadjigeorgiou, G.,Sakka, P.,Maraki, M.,Scarmeas, N. Adherence to the Mediterranean diet and incident frailty: Results from a longitudinal study. Maturitas. 2022. 162:44–51. doi: 10.1016/j.maturitas.2022.05.001 35561586 | Outcome
170 | Osawa, Y.,Arai, Y.,Takayama, M.,Hirata, T.,Kawasaki, M.,Abe, Y.,Iinuma, T.,Sasaki, S.,Hirose, N. Identification of dietary patterns and their relationships with general and oral health in the very old. Asia Pac J Clin Nutr. 2017. 26:262–270. doi: 10.6133/apjcn.022016.02 28244704 | Study design
171 | Otsuka, R.,Kato, Y.,Nishita, Y.,Tange, C.,Nakamoto, M.,Tomida, M.,Imai, T.,Ando, F.,Shimokata, H.,Suzuki, T. Dietary diversity and 14-year decline in higher-level functional capacity among middle-aged and elderly Japanese. Nutrition. 2016. 32:784–9. doi: 10.1016/j.nut.2016.01.022 27068882 | Intervention/exposure
172 | Ozawa, M.,Ninomiya, T.,Ohara, T.,Doi, Y.,Uchida, K.,Shirota, T.,Yonemoto, K.,Kitazono, T.,Kiyohara, Y. Dietary patterns and risk of dementia in an elderly Japanese population: the Hisayama Study. Am J Clin Nutr. 2013. 97:1076–82. doi: 10.3945/ajcn.112.045575 23553168 | Data overlap
173 | Ozawa, M.,Shipley, M.,Kivimaki, M.,Singh-Manoux, A.,Brunner, E. J. Dietary pattern, inflammation and cognitive decline: The Whitehall II prospective cohort study. Clin Nutr. 2017. 36:506–512. doi: 10.1016/j.clnu.2016.01.013 26874911 | Data overlap
174 | Park, J. E.,Jeon, S. Y.,Kim, S. A.,Kim, J. H.,Kim, S. H.,Lee, K. W.,Hwang, Y. J.,Jung, G.,Suk, H. W.,Park, S., A Multidomain Intervention for Modifying Lifestyle Habits Reduces the Dementia Risk in Community-Dwelling Older Adults: a Single-Blinded Randomized Controlled Pilot Study. Journal of Alzheimer's disease. 2019. 70:51–60. doi: 10.3233/JAD190016 | Intervention/exposure, Study duration <4 wk
175 | Parrott, M. D.,Shatenstein, B.,Ferland, G.,Payette, H.,Morais, J. A..Belleville, S.,Kergoat, M. J.,Gaudreau, P.,Greenwood, C. E. Relationship between diet quality and cognition depends on socioeconomic position in healthy older adults. J Nutr. 2013. 143:1767–73. doi: 10.3945/jn.113.181115 23986363 | Data overlap
176 | Pase, M. P.,Beiser, A.,Enserro, D.,Xanthakis, V.,Aparicio, H.,Satizabal, C. L.,Himali, J. J.,Kase, C. S.,Vasan, R. S.,DeCarli, C.,Seshadri, S. Association of Ideal Cardiovascular Health With Vascular Brain Injury and Incident Dementia. Stroke. 2016. 47:1201–6. doi: 10.1161/STROKEAHA.115.012608 27073239 | Intervention/exposure
177 | Pearson, K. E.,Wadley, V. G.,McClure, L. A.,Shikany, J. M.,Unverzagt, F. W.,Judd, S. E.. Dietary patterns are associated with cognitive function in the REasons for Geographic And Racial Differences in Stroke (REGARDS) cohort. J Nutr Sci. 2016. 5:e38. doi: 10.1017/jns.2016.27 27752305 | Data overlap
178 | Power, S. E.,O'Connor, E. M.,Ross, R. P.,Stanton, C.,O'Toole, P. W.,Fitzgerald, G. F.,Jeffery, I. B. Dietary glycaemic load associated with cognitive performance in elderly subjects. Eur J Nutr. 2015. 54:557–68. doi: 10.1007/S00394-014-0737-5 25034880 | Study design
179 | Prinelli, F..Fratiglioni, L.,Musicco, M.,Johansson, l.,Adorni, F.,Shakersain, B.,Rizzuto, D.,Xu, W. The impact of nutrient-based dietary patterns on cognitive decline in older adults. Clin Nutr. 2019. 38:2813–2820. doi: 10.1016/j.clnu.2018.12.012 30591381 | Intervention/exposure
180 | Psaltopoulou, T.,Kyrozis, A.,Stathopoulos, P.,Trichopoulos, D.,Vassilopoulos, D.,Trichopoulou, A. Diet, physical activity and cognitive impairment among elders: the EPICGreece cohort (European Prospective Investigation into Cancer and Nutrition). Public Health Nutr. 2008. 11:1054–62. doi: 10.1017/S1368980007001607 18205988 | Data overlap
181 | Psaltopoulou, T.,Sergentanis, T. N. Mediterranean diet may reduce Alzheimer's risk. Evidence based medicine. 2015. 20:202–202. doi: 10.1136/ebmed-2015-110237 26337936 | Publication status
182 | Qin, B.,Adair, L. S.,Plassman, B. L.,Batis, C.,Edwards, L. J.,Popkin, B. M.,Mendez, M. A. Dietary Patterns and Cognitive Decline Among Chinese Older Adults. Epidemiology. 2015. 26:758–68. doi: 10.1097/EDE.0000000000000338 26133024 | Country
183 | R Li, R Li, J Xie, J Chen, S Liu, A Pan, G Liu. Associations of socioeconomic status and healthy lifestyle with incident early-onset and late-onset dementia: a prospective cohort study. The lancet. Healthy longevity. 2023. 4(12):e693–e702. doi: 10.1016/S26667568(23)00211-8 38042162 | Intervention/exposure
184 | Rainey-Smith, S. R.,Gu, Y.,Gardener, S. L.,Doecke, J. D.,Villemagne, V. L.,Brown, B. M.,Taddei, K.,Laws, S. M.,Sohrabi, H. R.,Weinborn, M.,Ames, D.,Fowler, C.,Macaulay, S. L.,Maruff, P.,Masters, C. L.,Salvado, O.,Rowe, C. C.,Scarmeas, N.,Martins, R. N., Mediterranean diet adherence and rate of cerebral Aβ-amyloid accumulation: Data from the Australian Imaging, Biomarkers and Lifestyle Study of Ageing. Transl Psychiatry. 2018. 8:238. doi: 10.1038/S41398-018-0293-5 30375373 | Outcome
185 | Richard, E. L.,Laughlin, G. A.,Kritz-Silverstein, D.,Reas, E. T.,Barrett-Connor, E.,McEvoy, L. K. Dietary Patterns and Cognitive Function among Older Community-Dwelling Adults. Nutrients. 2018. 10:#pages#. doi: 10.3390/nu10081088 | Data overlap
186 | Rizza, W.,De Gara, L.,Antonelli Incalzi, R.,Pedone, C. Prototypical versus contemporary Mediterranean Diet. Clin Nutr ESPEN. 2016. 15:44–48. doi: 10.1016/j.clnesp.2016.06.007 28531783 | Study design, Outcome
187 | Roberts, R. O.,Geda, Y. E.,Cerhan, J. R.,Knopman, D. S.,Cha, R. H.,Christianson, T. J.,Pankratz, V. S.,Ivnik, R. J.,Boeve, B. F.,O'Connor, H. M.,Petersen, R. C. Vegetables, unsaturated fats, moderate alcohol intake, and mild cognitive impairment. Dement Geriatr Cogn Disord. 2010. 29:413–23. doi: 10.1159/000305099 20502015 | Data overlap
188 | Rodriguez-Espinosa, N.,Moro Miguel, A.,Rodriguez-Perez, M. D. C.,Almeida-Gonzalez, D.,Cabrera de Leon, A. Adherence to the Mediterranean diet and waist-to-hip ratio in middle-aged postmenopausal women are the main factors associated with semantic verbal fluency 12 years later. Front Nutr. 2023. 10:1106629. doi: 10.3389/fnut.2023.1106629 37255942 | Intervention/exposure
189 | Rubin, R. Fish-Rich Mediterranean Diet Associated With Higher Cognition. Jama. 2020. 323:1998. doi: 10.1001/jama.2020.7061 | Study design
190 | Ruffman, T.,Zhang, J.,Taumoepeau, M.,Skeaff, S. Your Way to a Better Theory of Mind: A Healthy Diet Relates to Better Faux Pas Recognition in Older Adults. Exp Aging Res. 2016. 42:279–88. doi: 10.1080/0361073X.2016.1156974 27070046 | Study design
191 | Russin, K. J.,Nair, K. S.,Montine, T. J.,Baker, L. D.,Craft, S. Diet Effects on Cerebrospinal Fluid Amino Acids Levels in Adults with Normal Cognition and Mild Cognitive Impairment. J Alzheimers Dis. 2021. 84:843–853. doi: 10.3233/JAD-210471 34602470 | Study duration <4 wk
192 | S Gregory, K Blennow, CW Ritchie, OM Shannon, EJ Stevenson, G Muniz-Terrera. Mediterranean diet is associated with lower white matter lesion volume in Mediterranean cities and lower cerebrospinal fluid Aβ in non-Mediterranean cities in the EPAD LCS cohort. Neurobiology of aging. 2023. 131:29–38. doi: 10.1016/j.neurobiolaging.2023.07.012 37572525 | Study design
193 | Sakurai, K.,Okada, E.,Anzai, S.,Tamura, R.,Shiraishi, I.,Inamura, N.,Kobayashi, S.,Sato, M.,Matsumoto, T.,Kudo, K.,Sugawara, Y.,Hisatsune, T. Protein-Balanced Dietary Habits Benefit Cognitive Function in Japanese Older Adults. Nutrients. 2023. 15(3):770. doi: 10.3390/nu15030770 36771475 | Study design
194 | Samieri, C.,Grodstein, F.,Rosner, B. A.,Kang, J. H.,Cook, N. R.,Manson, J. E.,Buring, J. E.,Willett, W. C.,Okereke, O. I. Mediterranean diet and cognitive function in older age. Epidemiology. 2013. 24:490–9. doi: 10.1097/EDE.0b013e318294a065 23676264 | Data overlap
195 | Samieri, C.,Okereke, O. I.,E. Devore E,Grodstein, F. Long-term adherence to the Mediterranean diet is associated with overall cognitive status, but not cognitive decline, in women. J Nutr. 2013. 143:493–9. doi: 10.3945/jn.112.169896 23365105 | Data overlap
196 | Samieri, C.,Perier, M. C.,Gaye, B.,Proust-Lima, C.,Helmer, C.,Dartigues, J. F.,Berr, C.,Tzourio, C.,Empana, J. P. Association of cardiovascular health level in older age with cognitive decline and incident dementia. JAMA - Journal of the American Medical Association. 2018. 320:657–664. doi: 10.1001/jama.2018.11499 30140876 | Intervention/exposure
197 | Sandison, H.,Callan, N. G. L.,Rao, R. V.,Phipps, J.,Bradley, R. Observed Improvement in Cognition During a Personalized Lifestyle Intervention in People with Cognitive Decline. J Alzheimers Dis. 2023. 94:993–1004. doi: 10.3233/JAD-230004 37355891 | Participant health status
198 | Scarmeas, N.,Luchsinger, J. A.,Stern, Y.,Gu, Y.,He, J.,DeCarli, C.,Brown, T.,Brickman, A. M. Mediterranean diet and magnetic resonance imaging-assessed cerebrovascular disease. Ann Neurol. 2011. 69:257–68. doi: 10.1002/ana.22317 21387371 | Outcome
199 | Scarmeas, N.,Mayeux, R.,Stern, Y.,Luchsinger, J. A. Mediterranean diet and Alzheimer's disease. 2007. 12:105–110. | Study design
200 | Scarmeas, N.,Stern, Y.,Mayeux, R.,Manly, J. J.,Schupf, N.,Luchsinger, J. A. Mediterranean diet and mild cognitive impairment. Arch Neurol. 2009. 66:216–25. doi: 10.1001/archneurol.2008.536 19204158 | Data overlap
201 | Scarmeas, N.,Stern, Y.,Tang, M. X.,Mayeux, R.,Luchsinger, J. A. Mediterranean diet and risk for Alzheimer's disease. Ann Neurol. 2006. 59:912–21. doi: 10.1002/ana.20854 16622828 | Data overlap
202 | Schulz, C. A.,Weinhold, L.,Schmid, M.,Nöthen, M. M.,Nöthlings, U. Analysis of associations between dietary patterns, genetic disposition, and cognitive function in data from UK Biobank. Eur J Nutr. 2023. 62:511–521. doi: 10.1007/s00394-022-02976-y 36152054 | Outcome
203 | Shakersain, B.,Rizzuto, D.,Larsson, S. C.,Faxén-Irving, G.,Fratiglioni, L.,Xu, W. L. The Nordic Prudent Diet Reduces Risk of Cognitive Decline in the Swedish Older Adults: A Population-Based Cohort Study. Nutrients. 2018. 10(2):229. doi: 10.3390/nu10020229 29462973 | Data overlap
204 | Shakersain, B.,Rizzuto, D.,Wang, H. X.,Faxén-Irving, G.,Prinelli, F.,Fratiglioni, L.,Xu, W. An Active Lifestyle Reinforces the Effect of a Healthy Diet on Cognitive Function: A PopulationBased Longitudinal Study. Nutrients. 2018. 10(9): 1297. doi: 10.3390/nu10091297 30217035 | Data overlap
205 | Shakersain, B.,Santoni, G.,Larsson, S. C.,Faxén-Irving, G.,Fastbom, J.,Fratiglioni, L.,Xu, W. Prudent diet may attenuate the adverse effects of Western diet on cognitive decline. Alzheimers Dement. 2016. 12:100–109. doi: 10.1016/j.jalz.2015.08.002 26342761 | Data overlap
206 | Shannon, O. M.,Stephan, B. C. M.,Granic, A.,Lentjes, M.,Hayat, S.,Mulligan, A.,Brayne, C.,Khaw, K. T.,Bundy, R.,Aldred, S.,Hornberger, M.,Paddick, S. M.,Muniz-Tererra, G.,Minihane, A. M..Mathers, J. C.,Siervo, M. Mediterranean diet adherence and cognitive function in older UK adults: the European Prospective Investigation into Cancer and Nutrition-Norfolk (EPIC-Norfolk) Study. Am J Clin Nutr. 2019. 110:938–948. doi: 10.1093/ajcn/nqz114 31204785 | Data overlap
207 | Shatenstein, B.,Ferland, G.,Belleville, S.,Gray-Donald, K.,Kergoat, M. J.,Morais, J.,Gaudreau, P.,Payette, H.,Greenwood, C. Diet quality and cognition among older adults from the NuAge study. Exp Gerontol. 2012. 47:353–60. doi: 10.1016/j.exger.2012.02.002 22386581 | Data overlap
208 | Sheng, L. T.,Jiang, Y. W.,Feng, L.,Pan, A.,Koh, W. P. Dietary Total Antioxidant Capacity and Late-Life Cognitive Impairment: The Singapore Chinese Health Study. J Gerontol A Biol Sci MedSci. 2022. 77:561–569. doi: 10.1093/gerona/glab100 | Intervention/exposure
209 | Shimizu, K.,Takeda, S.,Noji, H.,Hirose, N.,Ebihara, Y.,Arai, Y.,Hamamatsu, M.,Nakazawa, S.,Gondo, Y.,Konishi, K. Dietary patterns and further survival in Japanese centenarians. J Nutr Sci Vitaminol (Tokyo). 2003. 49:133–8. doi: 10.3177/jnsv.49.133 12887160 | Outcome
210 | Shin, D.,Lee, K. W.,Kim, M. H.,Kim, H. J.,An, Y. S.,Chung, H. K. Identifying Dietary Patterns Associated with Mild Cognitive Impairment in Older Korean Adults Using Reduced Rank Regression. Int J Environ Res Public Health. 2018. 15(1): 100. doi: 10.3390/ijerph15010100 29315276 | Study design
211 | Shiri, R.,Väänänen, A.,Mattila-Holappa, P.,Kauppi, K.,Borg, P. The Effect of Healthy Lifestyle Changes on Work Ability and Mental Health Symptoms: A Randomized Controlled Trial. International Journal of Environmental Research and Public Health. 2022. 19(20):13206. doi: 10.3390/ijerph192013206 36293787 | Study duration 8–12 wk
212 | Sindi, S.,Kåreholt, I.,Eskelinen, M.,Hooshmand, B.,Lehtisalo, J.,Soininen, H.,Ngandu, T.,Kivipelto, M. Healthy Dietary Changes in Midlife Are Associated with Reduced Dementia Risk Later in Life. Nutrients. 2018. 10(11):1649. doi: 10.3390/nu10111649 30400288 | Intervention/exposure
213 | Skoczek-Rubihska, A.,Muzsik-Kazimierska, A.,Chmurzynska, A.,Jamka, M.,Walkowiak, J.,Bajerska, J. Inflammatory Potential of Diet Is Associated with Biomarkers Levels of Inflammation and Cognitive Function among Postmenopausal Women. Nutrients. 2021. 13(7):2323. doi: 10.3390/nu13072323 34371834 | Study design
214 | Small, G. W.,Silverman, D. H.,Siddarth, P.,Ercoli, L. M.,Miller, K. J.,Lavretsky, H.,Wright, B. C.,Bookheimer, S. Y.,Barrio, J. R.,Phelps, M. E Effects of a 14-day healthy longevity lifestyle program on cognition and brain function. Am J Geriatr Psychiatry. 2006. 14:538–45. doi: 10.1097/01.JGP.0000219279.72210.ca 16731723 | Study duration <4 wk
215 | Smith, P. J.,Mabe, S. M..Sherwood, A.,Doraiswamy, P. M.,Welsh-Bohmer, K. A.,Burke, J. R.,Kraus, W. E.,Lin, P. H.,Browndyke, J. N.,Babyak, M. A.,Hinderliter, A. L.,Blumenthal, J. A. Metabolic and Neurocognitive Changes Following Lifestyle Modification: Examination of Biomarkers from the ENLIGHTEN Randomized Clinical Trial. J Alzheimers Dis. 2020. 77:1793–1803. doi: 10.3233/JAD-200374 32925039 | Intervention/exposure, Outcome
216 | Smyth, A.,Dehghan, M.,O'Donnell, M.,Anderson, C.,Teo, K.,Gao, P.,Sleight, P.,Dagenais, G.,Probstfield, J. L.,Mente, A.,Yusuf, S. Healthy eating and reduced risk of cognitive decline: A cohort from 40 countries. Neurology. 2015. 84:2258–65. doi: 10.1212/WNL.0000000000001638 25948720 | Data overlap
217 | Soldevila-Domenech, N.,Forcano, L.,Vintró-Alcaraz, C.,Cuenca-Royo, A.,Pintó, X.,JiménezMurcia, S.,García-Gavilán, J. F.,Nishi, S. K.,Babio, N.,Gomis-González, M.,Corella, D.,Sorlí, J. V.,Fernandez-Carrión, R.,Martínez-González, MÁ,Marti, A.,Salas-Salvadó, J.,Castañer, 0.,Fernández-Aranda, F.,Torre, R. Interplay between cognition and weight reduction in individuals following a Mediterranean Diet: Three-year follow-up of the PREDIMED-Plus trial. Clin Nutr. 2021.40:5221–5237. doi: 10.1016/j.clnu.2021.07.020 34474192 | No key confounders accounted for
218 | Solfrizzi, V.,Frisardi, V.,Seripa, D.,Logroscino, G. Imbimbo, B. P. D'Onofrio, G.,Addante, F.,Sancarlo, D.,Cascavilla, L.,Pilotto, A.,Panza, F. Mediterranean diet in predementia and dementia syndromes. Current Alzheimer Research. 2011.8:520–542. doi: 10.2174/156720511796391809 21605047 | Study design
219 | Solomon, A.,Turunen, H.,Ngandu, T.,Peltonen, M.,Levalahti, E.,Helisalmi, S.,Antikainen, R.,Backman, L.,Hanninen, T.,Jula, A.,,. Effect of the apolipoprotein e genotype on cognitive change during a multidomain lifestyle intervention a subgroup analysis of a randomized clinical trial. JAMA neurology. 2018. 75:462–470. doi: 10.1001/jamaneurol.2017.4365 29356827 | Intervention/exposure
220 | Song, Y.,Cheng, F.,Du, Y.,Zheng, J.,An, Y.,Lu, Y. Higher Adherence to the AMED, DASH, and CHFP Dietary Patterns Is Associated with Better Cognition among Chinese Middle-Aged and Elderly Adults. Nutrients. 2023. 15(18):3974. doi: 10.3390/nu15183974 37764758 | Country
221 | Sotos-Prieto, M.,Ortolá, R.,López-García, E.,Rodríguez-Artalejo, F.,García-Esquinas, E. Adherence to the Mediterranean Diet and Physical Resilience in Older Adults: The SeniorsENRICA Cohort. J Gerontol A Biol Sci Med Sci. 2021.76:505–512. doi: 10.1093/gerona/glaa277 33152061 | Outcome
222 | Spanaki, C.,Rodopaios, N. E.,Koulouri, A.,Pliakas, T.,Papadopoulou, S. K.,Vasara, E.,Skepastianos, P.,Serafeim, T.,Boura, I.,Dermitzakis, E.,Kafatos, A. The Christian Orthodox Church Fasting Diet Is Associated with Lower Levels of Depression and Anxiety and a Better Cognitive Performance in Middle Life. Nutrients. 2021. 13(2):627. doi: 10.3390/nu13020627 33671993 | Intervention/exposure
223 | Sugawara, N.,Yasui-Furukori, N.,Umeda, T.,Tsuchimine, S.,Kaneda, A.,Tsuruga, K. Iwane, K.,Okubo, N.,Takahashi, I.,Kaneko, S.. Relationship between dietary patterns and cognitive function in a community-dwelling population in Japan. Asia Pac J Public Health. 2015. 27:Np2651–60. doi: 10.1177/1010539513490194 23858514 | Study design
224 | Sun, K.,Hu, H.,Yang, C.,Wang, L.,Ai, Y.,Dong, X.,Shi, Y.,Li, M.,Yao, Q.,Zhang, Y. Dietary Intake is Positively Associated with Cognitive Function of a Chinese Older Adults Sample. J Nutr Health Aging. 2018. 22:805–810. doi: 10.1007/s12603-018-1048-y 30080224 | Study design
225 | Takeuchi, H.,Kawashima, R. Diet and Dementia: A Prospective Study. Nutrients. 2021. 13(12):4500. doi: 10.3390/nu13124500 | Intervention/exposure
226 | Tangney, C. C.,Kwasny, M. J.,Li, H.,Wilson, R. S.,Evans, D. A..Morris, M. C. Adherence to a Mediterranean-type dietary pattern and cognitive decline in a community population. Am J Clin Nutr. 2011.93:601–7. doi: 10.3945/ajcn.110.007369 21177796 | Data overlap
227 | Tanprasertsuk, J.,Scott, T. M.,Barbey, A. K.,Barger, K.,Wang, X. D.,Johnson, M. A.,Poon, L. W.,Vishwanathan, R.,Matthan, N. R.,Lichtenstein, A. H.,Ferland, G.,Johnson, E. J. Carotenoid-Rich Brain Nutrient Pattern Is Positively Correlated With Higher Cognition and Lower Depression in the Oldest Old With No Dementia. Front Nutr. 2021.8:704691. doi: 10.3389/fnut.2021.704691 34268331 | Intervention/exposure
228 | Tate Chinara, M. Examining the effect of a high quality dietary intervention on cognitive function in early adolescence. Dissertation abstracts international: section B: the sciences and engineering. 2017. 78:No Pagination Specified, doi: 10.7916/D8TQ61T5 | Outcome
229 | Thomas, A.,Lefèvre-Arbogast, S.,Féart, C.,Foubert-Samier, A.,Helmer, C.,Catheline, G.,Samieri, C. Association of a MIND Diet with Brain Structure and Dementia in a French Population. J Prev Alzheimers Dis. 2022. 9:655–664. doi: 10.14283/jpad.2022.67 36281669 | Publication status
230 | Titova, O. E.,Ax, E.,Brooks, S. J.,Sjögren, P.,Cederholm, T.,Kilander, L.,Kullberg, J.,Larsson, E. M.,Johansson, L.,Ahlström, H.,Lind, L.,Schiöth, H. B.,Benedict, C. Mediterranean diet habits in older individuals: associations with cognitive functioning and brain volumes. Exp Gerontol. 2013. 48:1443–8. doi: 10.1016/j.exger.2013.10.002 24126083 | Data overlap
231 | Tomata, Y.,Sugiyama, K.,Kaiho, Y.,Honkura, K.,Watanabe, T.,Zhang, S.,Sugawara, Y.,Tsuji, I.. Dietary Patterns and Incident Dementia in Elderly Japanese: The Ohsaki Cohort 2006 Study. J Gerontol A Biol Sci Med Sci. 2016. 71:1322–8. doi: 10.1093/gerona/glw117 27356978 | Data overlap
232 | Tor-Roca, A., S?nchez-Pla, A., Korosi, A., Pall?s, M., Lucassen, P.J., Castellano-Escuder, P., Aigner, L., Gonz?lez-Dom?nguez, R., Manach, C., Carmona, F., Vegas, E., Helmer, C., Feart, C., Lefevre-Arbogast, S., Neuffer, J., Lee, H., Thuret, S., Andres-Lacueva, C., Samieri, C., Urpi-Sarda, M. A Mediterranean Diet-Based Metabolomic Score and Cognitive Decline in Older Adults: A Case-Control Analysis Nested within the Three-City Cohort Study. Molecular nutrition & food research. 2023. 68(13):e2300271. doi: 10.1002/mnfr.202300271 37876144 | Intervention/exposure
233 | Tsai, H. J. Dietary patterns and cognitive decline in Taiwanese aged 65 years and older. Int J Geriatr Psychiatry. 2015. 30:523–30. doi: 10.1002/gps.4176 25043924 | Country
234 | Tsai, J. H.,Huang, C. F.,Lin, M. N.,Chang, C. E.,Chang, C. C.,Lin, C. L. Taiwanese Vegetarians Are Associated with Lower Dementia Risk: A Prospective Cohort Study. Nutrients. 2022. 14(3):588. doi: 10.3390/nu14030588 35276947 | Intervention/exposure
235 | Tsivgoulis, G.,Judd, S.,Letter, A. J.,Alexandrov, A. V.,Howard, G.,Nahab, F.,Unverzagt, F. W.,Moy, C.,Howard, V. J.,Kissela, B.,Wadley, V. G. Adherence to a Mediterranean diet and risk of incident cognitive impairment. Neurology. 2013. 80:1684–92. doi: 10.1212/WNL.0b013e3182904f69 23628929 | Data overlap
236 | Tsolaki, M.,Lazarou, E.,Kozori, M.,Petridou, N.,Tabakis, I.,Lazarou, I.,Karakota, M.,Saoulidis, I.,Melliou, E.,Magiatis, P. A Randomized Clinical Trial of Greek High Phenolic Early Harvest Extra Virgin Olive Oil in Mild Cognitive Impairment: The MICOIL Pilot Study. J Alzheimers Dis. 2020. 78:801–817. doi: 10.3233/JAD-200405 33044178 | Intervention/exposure
237 | Tussing-Humphreys, L.,Lamar, M.,McLeod, A.,Schiffer, L.,Blumstein, L.,Dakers, R.,Karstens, A.,Hemphill, N. O. N.,Strahan, D.,Siegel, L.,Flack, J. S.,Antonic, M.,Restrepo, L.,Berbaum, M.,Fitzgibbon, M. Effect of Mediterranean diet and Mediterranean diet plus calorie restriction on cognition, lifestyle, and cardiometabolic health: A randomized clinical trial. Prev Med Rep. 2022. 29:101955. doi: 10.1016/j.pmedr.2022.101955 36161108 | Outcome
238 | Valls-Pedret, C.,Lamuela-Raventós, R. M.,Medina-Remón, A.,Quintana, M.,Corella, D.,Pintó, X.,Martínez-González, MÁ,Estruch, R.,Ros, E. Polyphenol-rich foods in the Mediterranean diet are associated with better cognitive function in elderly subjects at high cardiovascular risk. J Alzheimers Dis. 2012. 29:773–82. doi: 10.3233/JAD-2012-111799 22349682 | Intervention/exposure
239 | Valls-Pedret, C.,Sala-Vila, A.,Serra-Mir, M.,Corella, D.,de la Torre, R.,Martínez-González, MÁ,Martínez-Lapiscina, E. H.,Fitó, M.,Pérez-Heras, A.,Salas-Salvadó, J.,Estruch, R.,Ros, E. Mediterranean Diet and Age-Related Cognitive Decline: A Randomized Clinical Trial. JAMA Intern Med. 2015. 175:1094–1103. doi: 10.1001/jamainternmed.2015.1668 25961184 | Data overlap
240 | van Soest, A. P. M.,Hermes, G. D. A.,Berendsen, A. A. M.,van de Rest, O.,Zoetendal, E. G.,Fuentes, S.,Santoro, A.,Franceschi, C.,de Groot, Lcpgm,de Vos, W. M. Associations between Pro- and Anti-Inflammatory Gastro-Intestinal Microbiota, Diet, and Cognitive Functioning in Dutch Healthy Older Adults: The NU-AGE Study. Nutrients. 2020. 12(11):3471. doi: 10.3390/nu12113471 33198235 | Intervention/exposure
241 | Vercambre, M. N.,Boutron-Ruault, M. C.,Ritchie, K.,Clavel-Chapelon, F.,Berr, C. Long-term association of food and nutrient intakes with cognitive and functional decline: a 13-year follow-up study of elderly French women. Br J Nutr. 2009. 102:419–27. doi: 10.1017/S0007114508201959 19203415 | Intervention/exposure
242 | Vicinanza, R.,Bersani, F. S.,D'Ottavio, E.,Murphy, M.,Bernardini, S.,Crisciotti, F.,Frizza, A.,Mazza, V.,Biondi, M.,Troisi, G.,Cacciafesta, M. Adherence to Mediterranean diet moderates the association between multimorbidity and depressive symptoms in older adults. Archives of Gerontology and Geriatrics. 2020. 88:104022. doi: 10.1016/j.archger.2020.104022 32109694 | Study design
243 | Voortman, T.,Kiefte-de Jong, J. C.,Ikram, M. A.,Stricker, B. H.,van Rooij, F. J. A.,Lahousse, L.,Tiemeier, H.,Brusselle, G. G.,Franco, O. H.,Schoufour, J. D. Adherence to the 2015 Dutch dietary guidelines and risk of non-communicable diseases and mortality in the Rotterdam Study. Eur J Epidemiol. 2017. 32:993–1005. doi: 10.1007/s10654-017-0295-2 28825166 | Data overlap
244 | Wade, A. T.,Davis, C. R.,Dyer, K. A.,Hodgson, J. M.,Woodman, R. J.,Keage, H. A. D.,Murphy, K. J. A Mediterranean Diet with Fresh, Lean Pork Improves Processing Speed and Mood: Cognitive Findings from the MedPork Randomised Controlled Trial. Nutrients. 2019. 11(7):1521. doi: 10.3390/nu11071521 31277446 | Outcome
245 | Wade, A. T.,Davis, C. R.,Dyer, K. A.,Hodgson, J. M.,Woodman, R. J.,Keage, H. A. D.,Murphy, K. J. A Mediterranean diet supplemented with dairy foods improves mood and processing speed in an Australian sample: results from the MedDairy randomized controlled trial. Nutr Neurosci. 2020. 23:646–658. doi: 10.1080/1028415X.2018.1543148 30409085 | Study duration 8–12 wk
246 | Wagner, M.,Grodstein, F. Patterns of lifestyle behaviours from mid- through later-life in relation to exceptional episodic memory performance in older women: the Nurses' Health Study. Age Ageing. 2022. 51(5):afac102. doi: 10.1093/ageing/afac102 35536880 | Outcome
247 | Wang, B.,Wang, N.,Sun, Y.,Tan, X.,Zhang, J.,Lu, Y. Association of Combined Healthy Lifestyle Factors With Incident Dementia in Patients With Type 2 Diabetes. Neurology. 2022. 99:e2336–e2345. doi: 10.1212/WNL.0000000000201231 36104282 | Intervention/exposure
248 | Wang, K.,Tang, W.,Hao, X.,Zhao, J. Ultra-processed food consumption and risk of dementia and Alzheimer's disease: Long-term results from the Framingham Offspring Study. Alzheimer's and Dementia. 2023. 19(12):5988. doi: 10.1002/alz.13351 | Publication status
249 | Wang, T.,Cao, S.,Li, D.,Chen, F.,Jiang, Q.,Zeng, J. Association between dietary patterns and cognitive ability in Chinese children aged 10–15 years: evidence from the 2010 China Family Panel Studies. BMC Public Health. 2021. 21:2212. doi: 10.1186/s12889-021-12209 34863128 | Study design
250 | Wang, X.,Li, T.,Ding, H.,Liu, Y.,Liu, X.,Yu, K.,Xiao, R.,Xi, Y. The role of dietary patterns and erythrocyte membrane fatty acid patterns on mild cognitive impairment. Front Nutr. 2022. 9:1005857. doi: 10.3389/fnut.2022.1005857 36407514 | Study design, Country
251 | Ward, N.A., Reid-McCann, R., Brennan, L., Cardwell, C.R., de Groot, C., Maggi, S., McCaffrey, N., McGuinness, B., McKinley, M.C., Noale, M., O'Neill, R.F., Prinelli, F., Sergi, G., Trevisan, C., Volkert, D., Woodside, J.V., McEvoy, C.T. Effects of PROtein enriched MEDiterranean Diet and EXercise on nutritional status and cognition in adults at risk of undernutrition and cognitive decline: the PROMED-EX Randomised Controlled Trial. BMJ open. 2023. 13:e070689. doi: 10.1136/bmjopen-2022-070689 | Study design, Publication status
252 | Wardle, J.,Rogers, P.,Judd, P.,Taylor, M. A.,Rapoport, L.,Green, M.,Nicholson Perry, K. Randomized trial of the effects of cholesterol-lowering dietary treatment on psychological function. Am J Med. 2000. 108:547–53. doi: 10.1016/s0002-9343(00)00330-2 10806283 | Intervention/exposure
253 | Wei, K.,Yang, J.,Lin, S.,Mei, Y.,An, N.,Cao, X.,Jiang, L.,Liu, C.,Li, C. Dietary Habits Modify the Association of Physical Exercise with Cognitive Impairment in Community-Dwelling Older Adults. J Clin Med. 2022. 11(17):5122. doi: 10.3390/jcm11175122 36079052 | Country
254 | Wengreen, H. J.,Neilson, C.,Munger, R.,Corcoran, C. Diet quality is associated with better cognitive test performance among aging men and women. J Nutr. 2009. 139:1944–9. doi: 10.3945/jn.109.106427 19675102 | Data overlap
255 | Wengreen, H.,Munger, R. G.,Cutler, A.,Quach, A.,Bowles, A.,Corcoran, C.,Tschanz, J. T.,Norton, M. C.,Welsh-Bohmer, K. A. Prospective study of Dietary Approaches to Stop Hypertension- and Mediterranean-style dietary patterns and age-related cognitive change: the Cache County Study on Memory, Health and Aging. Am J Clin Nutr. 2013. 98:1263–71. doi: 10.3945/ajcn.112.051276 24047922 | Data overlap
256 | Wesselman, L. M. P.,Doorduijn, A. S.,de Leeuw, F. A.,Verfaillie, S. C. J.,van Leeuwenstijn-Koopman, M.,Slot, R. E. R.,Kester, M. I.,Prins, N. D.,van de Rest, O.,de van der Schueren, M. A. E.,Scheltens, P.,Sikkes, S. A. M.,van der Flier, W. M. Dietary Patterns Are Related to Clinical Characteristics in Memory Clinic Patients with Subjective Cognitive Decline: The SCIENCe Project. Nutrients. 2019. 11(5):1057. doi: 10.3390/nu11051057 31083522 | Study design, Participant health status
257 | Wright, K. D.,Klatt, M. D.,Adams, I. R.,Nguyen, C. M.,Mion, L. C.,Tan, A.,Monroe, T. B.,Rose, K. M.,Scharre, D. W. Mindfulness in Motion and Dietary Approaches to Stop Hypertension (DASH) in Hypertensive African Americans. J Am Geriatr Soc. 2021. 69:773–778. doi: 10.1111/jgs.16947 33227157 | Study duration 8–12 wk
258 | Wu, J.,Song, X.,Chen, G. C.,Neelakantan, N.,van Dam, R. M.,Feng, L.,Yuan, J. M.,Pan, A.,Koh, W. P. Dietary pattern in midlife and cognitive impairment in late life: a prospective study in Chinese adults. Am J Clin Nutr. 2019. 110:912–920. doi: 10.1093/ajcn/nqz150 31374567 | Data overlap
259 | Wu, W.,Shang, Y.,Dove, A.,Guo, J.,Calderón-Larrañaga, A.,Rizzuto, D.,Xu, W. The Nordic prudent diet prolongs survival with good mental and physical functioning among older adults: The role of healthy lifestyle. Clin Nutr. 2021. 40:4838–4844. doi: 10.1016/j.clnu.2021.06.027 34358824 | Outcome
260 | X Xing, X Yang, J Chen, J Wang, B Zhang, Y Zhao, S Wang. Multimorbidity, healthy lifestyle, and the risk of cognitive impairment in Chinese older adults: a longitudinal cohort study. BMC public health. 2024. 24(1):46. doi: 10.1186/s12889-023-17551-1 38166903 | No key confounders accounted for
261 | Xia, X.,Qiu, C.,Rizzuto, D.,Grande, G.,Laukka, E. J.,Fratiglioni, L.,Guo, J.,Vetrano, D. L. The age-dependent association of Life's Simple 7 with transitions across cognitive states after age 60. Journal of Internal Medicine. 2023. 294:191–202. doi: 10.1111/joim.13657 37254588 | Intervention/exposure
262 | Xiu, L. L.,Wahlqvist, M. L.,Lee, M. S.,Chen, R. C. Cognitive impairment and limited dietary diversity or physical inactivity are conjoint precursors of incident diabetes more so in elderly women than men. Asia Pac J Clin Nutr. 2013. 22:635–45. doi: 10.6133/apjcn.2013.22.4.20 24231025 | Intervention/exposure, Outcome
263 | Xu, C.,Cao, Z.,Huang, X.,Wang, X. Associations of healthy lifestyle with depression and post-depression dementia: A prospective cohort study. J Affect Disord. 2023. 327:87–92. doi: 10.1016/j.jad.2023.01.111 36736794 | Comparator
264 | Xu, F.,Delmonico, M. J.,Lofgren, I. E.,Uy, K. M.,Maris, S. A.,Quintanilla, D.,Taetzsch, A. G.,Letendre, J.,Mahler, L. Effect of a Combined Tai Chi, Resistance Training and Dietary Intervention on Cognitive Function in Obese Older Women. J Frailty Aging. 2017. 6:167–171. doi: 10.14283/jfa.2017.16 28721435 | Intervention/exposure
265 | Xu, X.,Parker, D.,Shi, Z.,Byles, J.,Hall, J.,Hickman, L. Dietary Pattern, Hypertension and Cognitive Function in an Older Population: 10-Year Longitudinal Survey. Front Public Health. 2018. 6:201. doi: 10.3389/fpubh.2018.00201 30079333 | Country
266 | Ye, X.,Scott, T.,Gao, X.,Maras, J. E.,Bakun, P. J.,Tucker, K. L. Mediterranean diet, healthy eating index 2005, and cognitive function in middle-aged and older Puerto Rican adults. J Acad Nutr Diet. 2013. 113:276–81.e1–3. doi: 10.1016/j.jand.2012.10.014 23351632 | Study design
267 | Yokoyama, Y., Nofuji, Y., Seino, S., Abe, T., Murayama, H., Narita, M., Shinkai, S., Kitamura, A., Fujiwara, Y. Association of dietary variety with the risk for dementia: the Yabu cohort study. Public health nutrition. 2023. 26:2314. doi: 10.1017/S1368980023000824 37129033 | Intervention/exposure
268 | Young, H. A.,Freegard, G.,Benton, D. Mediterranean diet, interoception and mental health: Is it time to look beyond the 'Gut-brain axis'?. Physiol Behav. 2022. 257:113964. doi: 10.1016/j.physbeh.2022.113964 36130628 | Outcome
269 | Yu, F. N.,Hu, N. Q.,Huang, X. L.,Shi, Y. X.,Zhao, H. Z.,Cheng, H. Y. Dietary patterns derived by factor analysis are associated with cognitive function among a middle-aged and elder Chinese population. Psychiatry Res. 2018. 269:640–645. doi: 10.1016/j.psychres.2018.09.004 30216915 | Study design
270 | Zbeida, M.,Goldsmith, R.,Shimony, T.,Vardi, H.,Naggan, L.,Shahar, D. R. Mediterranean diet and functional indicators among older adults in non-Mediterranean and Mediterranean countries. J Nutr Health Aging. 2014. 18:411–8. doi: 10.1007/s12603-014-0003-9 24676323 | Study design
271 | Zellner, M.,Babeluk, R.,Jakobsen, L. H.,Gerner, C.,Umlauf, E.,Volf, I.,Roth, E.,Kondrup, J. A proteomics study reveals a predominant change in MaoB expression in platelets of healthy volunteers after high protein meat diet: Relationship to the methylation cycle. Journal of Neural Transmission. 2011. 118:653–662. doi: 10.1007/s00702-011-0617-6 21424576 | Intervention/exposure
272 | Zheng, J.,Zhou, R.,Li, F.,Chen, L.,Wu, K.,Huang, J.,Liu, H.,Huang, Z.,Xu, L.,Yuan, Z.,Mao, C.,Wu, X. Association between dietary diversity and cognitive impairment among the oldest-old: Findings from a nationwide cohort study. Clin Nutr. 2021. 40:1452–1462. doi: 10.1016/j.clnu.2021.02.041 33740515 | Country
273 | Zhong, W. F.,Song, W. Q.,Wang, X. M.,Li, Z. H.,Shen, D.,Liu, D.,Zhang, P. D.,Shen, Q. Q.,Liang, F.,Nan, Y.,Xiang, J. X.,Chen, Z. T.,Li, C.,Li, S. T.,Lv, X. G.,Lin, X. R.,Lv, Y. B.,Gao, X.,Kraus, V. B.,Shi, X. M.,Mao, C. Dietary Diversity Changes and Cognitive Frailty in Chinese Older Adults: A Prospective Community-Based Cohort Study. Nutrients. 2023. 15(17):3784. doi: 10.3390/nu15173784 37686817 | Country
274 | Zhu, A.,Chen, H.,Shen, J.,Wang, X.,Li, Z.,Zhao, A.,Shi, X.,Yan, L.,Zeng, Y.,Yuan, C.,Ji, J. S. Interaction between plant-based dietary pattern and air pollution on cognitive function: a prospective cohort analysis of Chinese older adults. Lancet Reg Health West Pac. 2022. 20:100372. doi: 10.1016/j.lanwpc.2021.100372 35028630 | Country
275 | Zhu, N.,Jacobs, D. R.,Meyer, K. A.,He, K.,Launer, L.,Reis, J. P.,Yaffe, K.,Sidney, S.,Whitmer, R. A.,Steffen, L. M. Cognitive function in a middle aged cohort is related to higher quality dietary pattern 5 and 25 years earlier: the CARDIA study. J Nutr Health Aging. 2015. 19:33–8. doi: 10.1007/s12603-014-0491-7 25560814 | Data overlap
276 | Zupo, R.,Griseta, C.,Battista, P.,Donghia, R.,Guerra, V.,Castellana, F.,Lampignano, L.,Bortone, I.,Lozupone, M.,Giannelli, G.,De Pergola, G.,Boeing, H.,Sardone, R.,Panza, F. Role of plant-based diet in late-life cognitive decline: results from the Salus in Apulia Study. Nutr Neurosci. 2022. 25:1300–1309. doi: 10.1080/1028415X.2020.1853416 33448914 | Study design