# Appendix 4 Literature search strategy

## Searches from existing reviews

The search conducted for an existing review identified articles published between January 1980 and February 2020. For the complete search documentation, refer to:

Boushey C, Ard J, Bazzano L, . Dietary Patterns and Neurocognitive Health: A Systematic Review. July 2020. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: 10.52570/NESR.DGAC2020.SR0106

## Search for the current review:

This search was first run on November 29, 2023, and then periodically run using NESR’s continuous evidence monitoring methods.^*^

* USDA Nutrition Evidence Systematic Review Branch. Chapter 10: Continuous Evidence Monitoring. In: USDA Nutrition Evidence Systematic Review: Methodology Manual. February 2023. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: https://nesr.usda.gov/methodology-overview.

### Database: PubMed

Provider: U.S. National Library of Medicine

Date(s) Searched: November 29, 2023 (initial search); November 29, 2023 – January 9, 2024 (continuous evidence monitoring)

Dates Covered: January 1, 1980 – January 9, 2024

Table A 4 Search for PubMed

Search # | Concept | String
#1 | Dietary Patterns | (“dietary pattern*”[tiab] OR “diet pattern*”[tiab] OR “eating pattern*”[tiab] OR “food pattern*”[tiab] OR “diet quality”[tiab] OR “dietary quality”[tiab] OR “diet variety”[tiab] OR “dietary variety”[tiab] OR “varied diet”[tiab] OR “dietary guideline*”[tiab] OR “dietary recommendation*”[tiab] OR “dietary intake*”[tiab] OR “eating style*”[tiab] OR “Diet, Mediterranean”[Mesh] OR “Mediterranean Diet*”[tiab] OR “Dietary Approaches To Stop Hypertension”[Mesh] OR “Dietary Approaches To Stop Hypertension Diet*”[tiab] OR “DASH diet*”[tiab] OR “Diet, Gluten-Free”[Mesh] OR “Gluten Free diet*”[tiab] OR “prudent diet*”[tiab] OR “Diet, Paleolithic”[Mesh] OR “Paleolithic Diet*”[tiab] OR “Diet, Vegetarian”[Mesh] OR “vegetarian diet*”[tiab] OR “vegan diet*”[tiab] OR “Diet, Healthy”[Mesh] OR “healthy diet*”[tiab] OR “plant based diet*”[tiab] OR “Diet, Western”[Mesh] OR “western diet*”[tiab] OR “Nordic Diet*”[tiab] OR “Okinawan diet*”[tiab] OR “Diet, Fat-Restricted”[Mesh] OR “Diet, High-Fat”[Mesh] OR “high-fat diet*”[tiab] OR “low fat diet*”[tiab] OR “Diet, Sodium-Restricted”[Mesh] OR “low-sodium diet*”[tiab] OR “low salt diet*”[tiab] OR “diet score*”[tiab] OR “diet quality score*”[tiab] OR “diet quality index*”[tiab] OR “diet quality indices”[tiab] OR kidmed[tiab] OR “diet index*”[tiab] OR “diet indices”[tiab] OR “dietary index*”[tiab] OR “dietary indices”[tiab] OR “food score*”[tiab] OR MedDietScore[tiab] OR “healthy eating index*”[tiab] OR “healthy eating indices”[tiab]); OR (guideline adherence*[tiab] AND (diet[tiab] OR dietary[tiab] OR food[tiab] OR beverage*[tiab] OR nutrition*[tiab]))
#2 | Cognitive Decline | “Cognition Disorders”[Mesh] OR “Cognition”[Mesh] OR cognition[tiab] OR metacognit*[tiab] OR meta-cognit*[tiab] OR neurocognit*[tiab] OR neuro-cognit*[tiab] OR “Dementia”[Mesh] OR dementia*[tiab] OR Alzheimer*[tiab] OR senility[tiab] OR senile[tiab] OR presenile[tiab] OR (cognit*[tiab] AND (function*[tiab] OR dysfunction*[tiab] OR declin*[tiab] OR deteriorat*[tiab] OR degenerat*[tiab] OR disorder*[tiab] OR dysfunction*[tiab] OR reduct*[tiab] OR impair*[tiab] OR deficit*[tiab] OR deficien*[tiab] OR progress*[tiab] OR perform*[tiab] OR abilit*[tiab]))
#3 | | #1 AND #2
#4 | Limits | #3 NOT (“Animals”[Mesh] NOT (“Animals”[Mesh] AND “Humans”[Mesh])); NOT (editorial[ptyp] OR comment[ptyp] OR commentary[tiab] OR news[ptyp] OR letter[ptyp] OR review[ptyp] OR systematic review[ptyp] OR systematic review[ti] OR meta-analysis[ptyp] OR meta-analysis[ti] OR meta-analyses[ti] OR protocol[ti] OR protocols[ti] OR retracted publication[ptyp] OR retraction of publication[ptyp] OR retraction of publication[tiab] OR retraction notice[ti] OR “retracted publication”[ti] OR “Congress”[Publication Type] OR “Consensus Development Conference”[Publication Type] OR “conference abstract*”[tiab] OR “conference proceeding*”[tiab] OR “conference paper*”[tiab] OR “practice guideline”[ptyp] OR “practice guideline”[ti]); Filters applied: English, from 1980/1/1 - 3000/12/12.

### Database: Embase

Provider: Elsevier

Date(s) Searched: November 29, 2023 (initial search); November 29, 2023 – January 9, 2024 (continuous evidence monitoring)

Dates Covered: January 1, 1980 – January 9, 2024

Table A 5 Search for Embase

Search # | Concept | String
#1 | Dietary Patterns | ‘dietary pattern’/exp OR ‘mediterranean diet’/exp OR ‘dash diet’/exp OR ‘gluten free diet’/exp OR ‘paleolithic diet’/de OR ‘vegetarian diet’/exp OR ‘healthy diet’/exp OR ‘western diet’/de OR ‘low carbohydrate diet’/exp OR ‘low fat diet’/de OR ‘lipid diet’/exp OR ‘protein restriction’/exp OR ‘sodium restriction’/exp OR ‘nordic diet’/de OR ‘protein diet’/exp OR ‘dietary pattern*’:ab,ti OR ‘diet pattern*’:ab,ti OR ‘eating pattern*’:ab,ti OR ‘food pattern*’:ab,ti OR ‘diet quality’:ab,ti OR ‘dietary quality’:ab,ti OR ‘diet variety’:ab,ti OR ‘dietary variety’:ab,ti OR ‘varied diet’:ab,ti OR ‘dietary guideline*’:ab,ti OR ‘dietary recommendation*’:ab,ti OR ‘dietary intake*’:ab,ti OR ‘eating style*’:ab,ti OR ‘mediterranean diet*’:ab,ti OR ‘dietary approaches to stop hypertension diet*’:ab,ti OR ‘dash diet*’:ab,ti OR ‘gluten free diet*’:ab,ti OR ‘prudent diet*’:ab,ti OR ‘paleolithic diet*’:ab,ti OR ‘vegetarian diet*’:ab,ti OR ‘vegan diet*’:ab,ti OR ‘healthy diet*’:ab,ti OR ‘plant based diet*’:ab,ti OR ‘western diet*’:ab,ti OR ‘nordic diet*’:ab,ti OR ‘okinawan diet*’:ab,ti OR ‘high-fat diet*’:ab,ti OR ‘low fat diet*’:ab,ti OR ‘low-sodium diet*’:ab,ti OR ‘low salt diet*’:ab,ti OR ‘diet score*’:ab,ti OR ‘diet quality score*’:ab,ti OR ‘diet quality index*’:ab,ti OR ‘diet quality indices’:ab,ti OR kidmed:ab,ti OR ‘diet index*’:ab,ti OR ‘diet indices’:ab,ti OR ‘dietary index*’:ab,ti OR ‘dietary indices’:ab,ti OR ‘food score*’:ab,ti OR meddietscore:ab,ti OR ‘healthy eating index*’:ab,ti OR ‘healthy eating indices’:ab,ti; OR ((‘guideline adherence*’ NEAR/2 (diet OR dietary OR food OR beverage* OR nutrition*)):ab,ti)
#2 | Cognitive Decline | ‘Cognition Defect’/exp OR ‘Cognition’/exp; OR cognition:ab,ti OR metacognit*:ab,ti OR meta-cognit*:ab,ti OR neurocognit*:ab,ti OR neuro-cognit*:ab,ti OR dementia*:ab,ti OR Alzheimer*:ab,ti OR senility:ab,ti OR senile:ab,ti OR presenile:ab,ti OR (cognit*:ab,ti AND (function*:ab,ti OR dysfunction*:ab,ti OR declin*:ab,ti OR deteriorat*:ab,ti OR degenerat*:ab,ti OR disorder*:ab,ti OR dysfunction*:ab,ti OR reduct*:ab,ti OR impair*:ab,ti OR deficit*:ab,ti OR deficien*:ab,ti OR progress*:ab,ti OR perform*:ab,ti OR abilit*:ab,ti))
#3 | | #1 AND #2
#4 | Limits | #3 AND ([article]/lim OR [article in press]/lim); NOT ([animals]/lim NOT ([animals]/lim AND [humans]/lim)); AND [english]/lim; NOT ([conference abstract]/lim OR [conference paper]/lim OR [conference review]/lim OR [editorial]/lim OR [erratum]/lim OR [letter]/lim OR [note]/lim OR ‘retraction of publication’:ab,ti OR ‘retraction notice’:ti OR ‘retracted publication’:ab,ti OR [review]/lim OR [systematic review]/lim OR [meta analysis]/lim OR protocol:ti OR protocols:ti OR ‘practice guideline’:ti) AND [1980-2024]/py

### Database: Cochrane Central Register of Controlled Trials (CENTRAL)

Provider: John Wiley & Sons

Date(s) Searched: November 29, 2023 (initial search); November 29, 2023 – January 9, 2024 (continuous evidence monitoring)

Dates Covered: January 1, 1980 – January 9, 2024

Table A 6 Search for Cochrane CENTRAL

Search # | Concept | String
#1 | Dietary Patterns | [mh “Diet, Mediterranean”] OR [mh “Dietary Approaches To Stop Hypertension”] OR [mh “Diet, Gluten-Free”] OR [mh “Diet, Paleolithic”] OR [mh “Diet, Vegetarian”] OR [mh “Diet, Healthy”] OR [mh “Diet, Western”] OR [mh “Diet, Fat-Restricted”] OR [mh “Diet, High-Fat”] OR [mh “Diet, Sodium-Restricted”] OR [mh “Guideline Adherence”]; OR (“dietary pattern” OR “dietary patterns” OR “diet pattern” OR ”diet patterns” OR “eating pattern” OR “eating patterns” OR “food pattern” OR “food patterns” OR “diet quality” OR “dietary quality” OR “diet variety” OR “dietary variety” OR “varied diet” OR “dietary guideline” OR “dietary guidelines” OR “dietary recommendation” OR “dietary recommendations” OR “dietary intake” OR “dietary intakes” OR “eating style” OR “eating styles” OR “Mediterranean Diet” OR “Mediterranean Diets” OR “Dietary Approaches To Stop Hypertension Diet” OR “Dietary Approaches To Stop Hypertension Diets” OR “DASH diet” OR “DASH diets” OR “Gluten Free diet” OR “Gluten Free diets” OR “prudent diet” OR “prudent diets” OR “Paleolithic Diet” OR “Paleolithic Diets” OR “vegetarian diet” OR “vegetarian diets” OR “vegan diet” OR “vegan diets” OR “healthy diet” OR “healthy diets” OR “plant based diet” OR “plant based diets” OR “Western diet” OR “Western diets” OR “Nordic Diet” OR “Nordic Diets” OR “Okinawan Diet” OR “Okinawan Diets” OR “high-fat diet” OR “high-fat diets” OR “low fat diet” OR “low fat diets” OR “low-sodium diet” OR “low-sodium diets” OR “low salt diet” OR “low salt diets” OR “diet score” OR “diet scores” OR “diet quality score” OR “diet quality scores” OR “diet quality index” OR “diet quality indexes” OR “diet quality indices” OR kidmed OR “diet index” OR “diet indexes” OR “diet indices” OR “dietary index” OR “dietary indexes” OR “dietary indices” OR “food score” OR “food scores” OR MedDietScore OR “healthy eating index” OR “healthy eating indexes” OR “healthy eating indices”):ti,ab,kw OR (“guideline adherence” NEAR/2 (diet OR dietary OR food OR beverage* OR nutrition*)):ti,ab,kw
#2 | Cognitive Decline | [mh “Cognition Disorders”] OR [mh “Cognition”] OR [mh “Dementia”]; OR (cognition OR metacognit* OR meta-cognit* OR neurocognit* OR neuro-cognit* OR dementia* OR Alzheimer* OR senility OR senile OR presenile OR (cognit* AND (function* OR dysfunction* OR declin* OR deteriorat* OR degenerat* OR disorder* OR dysfunction* OR reduct* OR impair* OR deficit* OR deficien* OR progress* OR perform* OR abilit*))):ti,ab,kw
#3 | | #1 AND #2; In Trials. Word variations searched. Publication Year from 1980 to 2024