# Appendix 3 Inclusion and exclusion criteria comparison between existing^*^ * Bouchey C, Ard J, Bazzano L, Heymsfield S, Mayer-Davis E, Sabaté J, Snetselaar L, Van Horn L, Schneeman B, English LK, Bates M, Callahan E, Venkatramanan S, Butera G, Terry N, Obbagy J. Dietary Patterns and Neurocognitive Health: A Systematic Review. July 2020. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: 10.52570/NESR.DGAC2020.SR0106 and update systematic reviews

Table A 3 Inclusion and exclusion criteria comparison between existing and updated systematic reviews for the research question: What is the relationship between dietary patterns consumed by adults and older adults and neurocognitive outcomes?

Category | Existing Review | Updated Review | Change and Rationale
Study design | [underlined: Included]:; - Randomized controlled trials; - Non-randomized controlled trials (including quasi-experimental and controlled before and after studies); - Quasi-experimental studies (i.e., prospective cohort studies); [underlined: Excluded]:; - Nested case-control studies; - Case-control studies; - Uncontrolled trials; - Case-control studies; - Cross-sectional studies; - Uncontrolled before-and-after studies; - Narrative reviews; - Systematic reviews; - Meta-analyses | [underlined: Included]:; - Randomized controlled trials; - Non-randomized controlled trials^†^; † Including quasi-experimental and controlled before-and-after studies; - Prospective cohort studies; - Retrospective cohort studies; - Nested case-control studies; [underlined: Excluded]:; - Uncontrolled trials^‡^; ‡ Including uncontrolled before-and-after studies; - Case-control studies; - Cross-sectional studies; - Ecological studies; - Narrative reviews; - Systematic reviews; - Meta-analyses; - Modeling and simulation studies; - Mendelian randomization studies | Study design criteria were modified to enable focus on a stronger body of evidence and to align with current NESR standards.
Publication date | [underlined: Included]:; - January 1980-January 2014; [underlined: Excluded]:; - Before January 1980 | [underlined: Included]:; - January 1980- January 2024^*^; * This review update date range encompasses the original systematic review date range, which included articles published from January 1980 to January 2014; [underlined: Excluded]:; - Before January 1980, after January 2024 | End of the date range is updated to extend from the end of search in the existing review to present
Population: Study participants | [underlined: Included]:; - Human; [underlined: Excluded]:; - Non-human | [underlined: Included]:; - Human; [underlined: Excluded]:; - Non-human | No change
Population: Life stage | [underlined: Included]:; - At intervention/exposure and outcome:; ○ Children, adolescents, adults, and older adults aged 2 years and older; [underlined: Excluded]:; - At intervention/exposure and outcome:; - Infants and toddlers (birth up to 24 months) | [underlined: Included]:; - At intervention/exposure:; ○ Children and adolescents (2 up to 19 years); ○ Adults and older adults (19 years and older); - At outcome:; ○ Adults and older adults (19 years and older); [underlined: Excluded]:; - At intervention/exposure and outcome:; ○ Infants and toddlers (birth up to 24 months); ○ Individuals during pregnancy; ○ Individuals during postpartum; - At outcome:; ○ Children and adolescents (2 up to 19 years); ○ Individuals during pregnancy | Population life stage was narrowed to focus on the most relevant populations of interest
Population: Health Status | [underlined: Included]:; - Subjects who were healthy or at elevated chronic disease risk; [underlined: Excluded]:; - Low-calorie intervention (defined as <1,600 kcal/day for women and <2,000 kcal/day for men); - Subjects who were hospitalized, diagnosed with disease, and/or receiving medical treatment | [underlined: Included]:; - Studies that [underlined: exclusively] enroll participants not diagnosed with a disease^*^; * Studies that enroll participants who are at risk for chronic disease will be included; - Studies that enroll [underlined: some] participants:; ○ diagnosed with a disease;; ○ and/or hospitalized for an illness, injury, or surgery; ○ with severe undernutrition, failure to thrive/underweight, stunting, or wasting;; ○ and/or with the outcome of interest; [underlined: Excluded]:; - Interventions designed to induce weight loss or treat overweight and obesity through energy-restriction/hypocaloric diets for the purposes of treating additional or other medical conditions; - Studies that [underlined: exclusively] enroll participants:; ○ diagnosed with a disease;^†^; † Studies that exclusively enroll participants with obesity will be included; ○ hospitalized for an illness, injury, or surgery;^‡^; ‡ Studies that exclusively enroll participants post-cesarean section will be included; ○ with severe undernutrition, failure to thrive/underweight, stunting, or wasting;; ○ and/or with the outcome of interest | No change other than to clarify intent
Intervention/exposure | [underlined: Included]:; - A description of the dietary pattern(s) consumed by subjects (i.e., the quantities, proportions, variety, or combination of different foods, drinks, and nutrients (when available) in diets, and the frequency with which they are habitually consumed), including, at a minimum, a description of the foods and beverages in the pattern); - Dietary patterns may be measured or derived using a variety of approaches, such as adherence to a priori patterns (indices/scores), data driven patterns (factor or cluster analysis), reduced rank regression, or other methods, including clinical trials.; [underlined: Excluded]:; - Studies that do not provide a description of the dietary pattern, which at minimum, must include the foods and beverages in the pattern (i.e., studies that examine a labeled dietary pattern, but do not describe the foods and beverages consumed). | [underlined: Included]:; - Studies that examine consumption of and/or adherence to a dietary pattern [i.e., the quantities, proportions, variety, or combination of different foods, drinks, and nutrients (when available) in diets, and the frequency with which they are habitually consumed], including, at a minimum, a description of the foods and beverages in the pattern of each intervention/exposure and comparator group; ○ Dietary patterns may be measured or derived using a variety of approaches, such as adherence to a priori patterns (indices/scores), data driven patterns (factor or cluster analysis), reduced rank regression, or other methods, including clinical trials; - Multi-component intervention in which the isolated effect of the dietary pattern on the outcome(s) of interest is provided or can be determined; [underlined: Excluded]:; - Studies that do not provide a description of the dietary pattern, which at minimum, must include the foods and beverages in the pattern (i.e., studies that examine a labeled dietary pattern, but do not describe the foods and beverages consumed in each intervention/exposure and comparator group).; - Multi-component intervention in which the isolated effect of the dietary pattern on the outcome(s) of interest is not analyzed or cannot be determined (e.g., due to multiple intervention components within groups). | Revisions were made to clarify the intent of the intervention/exposure and comparator criteria, but do not represent a change in how the criteria were applied
Comparator | [underlined: Included]:; - Adherence to a different dietary pattern; - Different levels of adherence to a dietary pattern; [underlined: Excluded]:; - N/A | [underlined: Included]:; - Consumption of and/or adherence to a different dietary pattern; - Different levels of consumption and/or adherence to a dietary pattern; [underlined: Excluded]:; - Consumption of and/or adherence to a similar dietary pattern of which only a specific component or food source is different between groups | No change other than to clarify the intent
Outcome(s) | [underlined: Included]:; - Dementia; - Cognitive impairment; - Alzheimer’s disease; [underlined: Excluded]:; - N/A | [underlined: Included]:; - Cognitive decline; - Mild cognitive impairment; - Dementia; - Alzheimer’s disease; [underlined: Excluded]:; - N/A | No change other than to clarify outcomes
Confounders | [underlined: Included:]; - n/a; [underlined: Excluded:]; - n/a | [underlined: Included:]; - Studies that control for one or more of the key confounders listed in the analytic framework; [underlined: Excluded:]; - Studies that do not control for any of the key confounders listed in the analytic framework | - Criteria were added to enable focus on a stronger body of evidence
Study duration (not applied to pregnancy and postpartum studies) | [underlined: Included]; - N/A; [underlined: Excluded]; - N/A | [underlined: Included]; - Intervention length ≥12 weeks; [underlined: Excluded]; - Intervention length <12 weeks | - Study duration criteria were modified to enable focus on a stronger body of evidence
Size of study groups | [underlined: Included]; - 30 participants per arm for interventions, or; - A power calculation included for interventions; - n≥ 1,000 for observational studies; [underlined: Excluded]; - Fewer than 30 participants per arm for interventions, and; - No power calculation reported for interventions; Fewer than 1,000 participants for observational studies | [underlined: Included]; - 30 participants per arm for interventions, or; - A power calculation included for interventions; [underlined: Excluded]; - Fewer than 30 participants per arm for interventions, and; No power calculation reported for interventions | - Sample size criteria for observational studies removed in order to expand the available body of evidence
Publication status | [underlined: Included]; - Peer-reviewed articles published in research journals; [underlined: Excluded]; - Non-peer reviewed articles, unpublished data or manuscripts, pre-prints, reports, and conference abstracts or proceedings | [underlined: Included]; - Peer-reviewed articles published in research journals; [underlined: Excluded]; - Non-peer reviewed articles, unpublished data or manuscripts, pre-prints, reports, and conference abstracts or proceedings | - No change
Language | [underlined: Included]; - Published in English; [underlined: Excluded]; - Not published in English | [underlined: Included]; - Published in English; [underlined: Excluded]; - Not published in English | - No change
Country^*^; * In order to determine the inclusion exclusion criteria for country, the Human Development classification was used. This classification is based on the Human Development Index (HDI) ranking from the year the study intervention occurred or data were collected (UN Development Program. HDI 1990–2017 HDRO calculations based on data from UNDESA (2017a), UNESCO Institute for Statistics (2018), United Nations Statistics Division (2018b), World Bank (2018b), Barro and Lee (2016) and IMF (2018). Available from: http://hdr.undp.org/en/data). If the study did not report the year in which the intervention occurred or data were collected, the HDI classification for the year of publication was applied. HDI values are available from 1980, and then from 1990 to present. If a study was conducted prior to 1990, the HDI classification from 1990 was applied. If a study was conducted in 2018 or 2019, the most current HDI classification was applied. When a country was not included in the HDI ranking, the current country classification from the World Bank was used instead (The World Bank. World Bank country and lending groups. Available from: https://datahelpdesk.worldbank.org/knowledgebase/articles/906519-world-country-and-lending-groups) | [underlined: Included]; - Subject populations from countries with high or very high human development, according to the 2011 Human Development Index; [underlined: Excluded]; Studies conducted in countries classified as medium or low on the 2011 Human Development Index. | [underlined: Included]; - Studies conducted in countries classified as high or very high on the Human Development Index the year(s) the intervention/exposure data were collected; [underlined: Excluded]; Studies conducted in countries classified as medium or low on the Human Development Index the year(s) the intervention/exposure data were collected | - NESR now applies the Human Development Index classification from the year in which the intervention/exposure data were collected