# Appendix 1 Abbreviations

Table A 1 List of abbreviations
Abbreviation: Full name
BMI: Body mass index
CVD: Cardiovascular disease
DASH: Dietary Approaches to Stop Hypertension
FFQ: Food frequency questionnaire
HDI: Human Development Index
HHS: United States Department of Health and Human Services
HTN: Hypertension
MIND: Mediterranean-Dash Intervention for Neurodegenerative Delay
MMSE: Mini Mental State Examination
NCC: Nested case-control study
NESR: Nutrition Evidence Systematic Review
PCS: Prospective cohort study
RCT: Randomized controlled trial
SEP: Socioeconomic position
SES: Socioeconomic status
TICS-M: Modified Telephone Interview for Cognitive Status
USDA: United States Department of Agriculture