# References of the articles included in the systematic review

1 Afonso L, Lopes C, Severo M, Bidirectional association between parental child-feeding practices and body mass index at 4 and 7 y of age. Am J Clin Nutr. Mar 2016;103(3):861–7.26843159
2 Arcan C, Hannan PJ, Fulkerson JA, Associations of home food availability, dietary intake, screen time and physical activity with BMI in young American-Indian children. Public Health Nutr. Jan 2013;16(1):146–55.22376987
3 Bergmeier H, Skouteris H, Horwood S, Hooley M, Richardson B. Child temperament and maternal predictors of preschool children's eating and body mass index. A prospective study. Appetite. Mar 2014;74:125–32.24345325
4 Eichler J, Schmidt R, Poulain T, Hiemisch A, Kiess W, Hilbert A. Stability, Continuity, and Bi-Directional Associations of Parental Feeding Practices and Standardized Child Body Mass Index in Children from 2 to 12 Years of Age. Nutrients. Jul 30 2019;11(8)
5 Faith MS, Berkowitz RI, Stallings VA, Kerns J, Storey M, Stunkard AJ. Parental feeding attitudes and styles and child body mass index: prospective analysis of a gene-environment interaction. Pediatrics. Oct 2004;114(4):e429–36.15466068
6 Gable S, Chang Y, Krull JL. Television watching and frequency of family meals are predictive of overweight onset and persistence in a national sample of school-aged children. J Am Diet Assoc. Jan 2007;107(1):53–61.17197271
7 Gregory JE, Paxton SJ, Brozovic AM. Maternal feeding practices, child eating behaviour and body mass index in preschool-aged children: a prospective analysis. Int J Behav Nutr Phys Act. Jun 28 2010;7:55.20579397
8 Gubbels JS, Kremers SPJ, Stafleu A, e Vries SI, Goldbohm RA. Association between parenting practices and children's dietary intake, activity behavior and development of body mass index: the KOALA Birth Cohort Study. International Journal of Behavioral Nutrition & Physical Activity. 2011;8:13p–13p.21342518
9 Guerrero AD, Chu L, Franke T, Kuo AA. Father Involvement in Feeding Interactions with Their Young Children. Am J Health Behav. Mar 2016;40(2):221–30.26931754
10 Hughes SO, Power TG, Connor TM, Orlet Fisher J, Chen T-A. Maternal Feeding Styles and Food Parenting Practices as Predictors of Longitudinal Changes in Weight Status in Hispanic Preschoolers from Low-Income Families. Journal of Obesity. 2016:1–9.
11 Hughes SO, Power TG, O'Connor TM, Fisher JO, Micheli NE, Papaioannou MA. Maternal feeding style and child weight status among Hispanic families with low-income levels: a longitudinal study of the direction of effects. Int J Behav Nutr Phys Act. Feb 15 2021;18(1):30.33588844
12 Jansen PW, Tharner A, van der Ende J, Feeding practices and child weight: is the association bidirectional in preschool children? Am J Clin Nutr. Nov 2014;100(5):1329–36.25332330
13 Karp SM, Barry KM, Gesell SB, Po'e EK, Dietrich MS, Barkin SL. Parental feeding patterns and child weight status for Latino preschoolers. Obes Res Clin Pract. Jan-Feb 2014;8(1):e88–97.24548581
14 Papaioannou MA, Power TG, O'Connor TM, Fisher JO, Micheli NE, Hughes SO. Child Weight Status: The Role of Feeding Styles and Highly Motivated Eating in Children. Children (Basel). Mar 4 2023;10(3)
15 Power TG, Beck AD, Fisher JO, Micheli N, O'Connor TM, Hughes SO. Observations of Maternal Feeding Practices and Styles and Young Children's Obesity Risk: A Longitudinal Study of Hispanic Mothers with Low Incomes. 17(1)
16 Quah PL, Ng JC, Fries LR, Longitudinal Analysis Between Maternal Feeding Practices and Body Mass Index (BMI): A Study in Asian Singaporean Preschoolers. Front Nutr. 2019;6:32.31001535
17 Rodgers RF, Paxton SJ, Massey R, Maternal feeding practices predict weight gain and obesogenic eating behaviors in young children: a prospective study. Int J Behav Nutr Phys Act. Feb 18 2013;10:24.23414332
18 Souto-Gallardo MC, Bacardí-Gascón M, Benjamin-Neelon S, Jiménez-Cruz A, Pineda-García G. Association of Food Parenting Practices on Child BMI z Score and Waist Circumference in Mexican Preschool Children After 1 Year of Follow-Up. J Nutr Educ Behav. Jan 2020;52(1):73–79.31734108
19 Bergmeier H, Aksan N, McPhie S, Mutually Responsive Orientation: A novel observational assessment of mother-child mealtime interactions. Appetite. Oct 1 2016;105:400–9.27317618
20 Bergmeier HJ, Skouteris H, Haycraft E, Haines J, Hooley M. Reported and observed controlling feeding practices predict child eating behavior after 12 months. J Nutr. Jun 2015;145(6):1311–6.25878204
21 Berkowitz Rl, Moore RH, Faith MS, Stallings VA, Krai TV, Stunkard AJ. Identification of an obese eating style in 4-year-old children born at high and low risk for obesity. Obesity (Silver Spring). Mar 2010;18(3):505 12.19779474
22 Campbell K, Andrianopoulos N, Hesketh K, Parental use of restrictive feeding practices and child BMI z-score. A 3-year prospective cohort study. Appetite. Aug 2010;55(1):84–8.20420869
23 Chong SY, Chittleborough CR, Mittinty MN, Smithers LG, Gregory T, Lynch JW. Associations of parental food-choice control and use of food to soothe with adiposity in childhood and adolescence. Appetite. 2017:71 77.
24 Derks IPM, Tiemeier H, Sijbrands EJG, Testing the direction of effects between child body composition and restrictive feeding practices: results from a population-based cohort. American Journal of Clinical Nutrition. 2017;106(3):783–790.28793987
25 Farrow CV, Haycraft E, Blissett JM. Observing Maternal Restriction of Food with 3(−)5-Year-Old Children: Relationships with Temperament and Later Body Mass Index (BMI). Int J Environ Res Public Health. Jun 15 2018;15(6)
26 Fulkerson JA, Hannan P, Rock BH, Smyth M, Himes JH, Story M. Food responsiveness, parental food control and anthropometric outcomes among young American Indian children: cross-sectional and prospective findings. Ethn Dis. Spring 2013;23(2):136–42.
27 Guivarch C, Cissé AH, Charles MA, Heude B, e Lauzon-Guillain B. Parental feeding practices as potential moderating or mediating factors in the associations between children's early and later growth. Int J Obes (Lond). Mar 2023;47(3):190–196.36653514
28 Jansen PW, Derks IPM, Mou Y, Associations of parents' use of food as reward with children's eating behaviour and BMI in a population-based cohort. Pediatric Obesity. 2020; 15(11): 1–10.
29 McPhie S, Skouteris H, Fuller-Tyszkiewicz M, Maternal predictors of preschool child-eating behaviours, food intake and body mass index: a prospective study. Early Child Development and Care. 2012;182(8):999–1014.
30 Rhee KE, Coleman SM, Appugliese DP, Maternal feeding practices become more controlling after and not before excessive rates of weight gain. Obesity (Silver Spring). Sep 2009;17(9):1724–9.19282827
31 Rodgers RF, Paxton SJ, McLean SA, Do maternal body dissatisfaction and dietary restraint predict weight gain in young pre-school children? A 1-year follow-up study. Appetite. Aug 2013;67:30–6.23541398
32 Faith MS, Heo M, Kral TV, Sherry B. Compliant eating of maternally prompted food predicts increased body mass index z-score gain in girls: results from a population-based sample. Child Obes. 2013;9:427–36.24094145
33 Fairley L, Santorelli G, Lawlor DA, The relationship between early life modifiable risk factors for childhood obesity, ethnicity and body mass index at age 3 years: findings from the Born in Bradford birth cohort study. BMC Obes. 2015;2:9.26217524
34 Kamdar N, Hughes SO, Chan W, Power TG, Meininger J. Indirect Effects of Food Insecurity on Body Mass Index Through Feeding Style and Dietary Quality Among Low-Income Hispanic Preschoolers. J Nutr Educ Behav. Jul - Aug 2019;51(7):876–884.30975581
35 Perez M, Winstone LK, Curci SG, Hernández JC, Somers JA, Luecken LJ. Longitudinal associations between early child weight gain, parent feeding, child self-regulation, and later child body mass index. Article in Press. Pediatric Obesity. 2021;doi: 10.1111/ijpo.12864
36 Worobey J, Trytko U. Associations Between Maternal Feeding Style and Child Overweight. ICAN: Infant, Child, & Adolescent Nutrition. 2014;6(4):216–220.