# Summary of conclusion statements and grades

The Committee answered the systematic review question, “What is the relationship between parental and caregiver feeding styles and practices and growth, body composition and risk of obesity?”, with the following conclusion statements.^*^ The grades reflect the strength of the evidence underlying the conclusion statements.

* A conclusion statement is carefully constructed, based on the evidence reviewed, to answer the systematic review question. A conclusion statement does not draw implications and should not be interpreted as dietary guidance.

### Structured feeding practices

Food parenting practices involving monitoring of children's eating by caregivers of children ages 2 to 6 years is not associated with outcomes related to growth. This conclusion statement is based on evidence graded as limited. (Grade: Limited)

A conclusion statement cannot be drawn about the relationship between food parenting practices by caregivers of children ages 2 to 6 years that structure children’s physical and social eating environments (e.g., availability of healthy foods, modeling of healthy eating behaviors, meal routines such as eating together as a family) and outcomes related to growth, body composition, and risk of obesity because there was not enough evidence available. (Grade: Grade Not Assignable)

### Controlling feeding practices

A conclusion statement cannot be drawn about the relationship between controlling feeding practices by caregivers of children ages 2 to 6 years and outcomes related to growth, body composition, and risk of obesity because there are substantial concerns with consistency in the body of evidence. (Grade: Grade Not Assignable)

### Autonomy supportive feeding practices

A conclusion statement cannot be drawn about the relationship between food parenting practices by caregivers of children ages 2 to 6 years that provide developmentally appropriate support for children's autonomy (e.g., responsive feeding, praise, child involvement in food and eating activities) and outcomes related to growth, body composition, and risk of obesity because there are few studies and substantial concerns with consistency in the body of evidence. (Grade: Grade Not Assignable)

### Feeding styles

A conclusion statement cannot be drawn about the relationship between feeding styles by caregivers of children ages 2 to 6 years and outcomes related to growth, body composition, and risk of obesity because there are substantial concerns with consistency in the body of evidence. (Grade: Grade Not Assignable)

## Research recommendations

- Conduct research within the U.S. with samples representing more diverse populations of caregivers with regard to sex and/or gender, relationship to the child (e.g., parent, grandparent, other relative), income level, race/ethnicity, and different family structures.
- Evaluate temporal ordering and causality of associations between food parenting and child GBCO outcomes using robust study designs that are adequately powered, specifically prospective cohort studies and controlled trials. Evaluating BMI z-scores outcomes at a single point in time does not provide a robust assessment of child growth.
- Utilize metrics of fat and lean body mass in future research. Growth, body composition, and obesity are challenging to quantify among children and tend to be captured using indicators with known limitations such as BMI and obesity classification.
- Refine existing measures and metrics using techniques like cognitive interviewing to develop meaningful tools to assess food parenting practices and feeding styles suitable across diverse populations. Questionnaires assessing caregivers’ food parenting styles and practices have been used in diverse populations but the meaning of those styles and practices within a particular culture, context, and environment is unclear. Further, parenting has a generational component; whether existing measures reflect current norms and practices around feeding young children warrants consideration.
- Conduct research to accurately capture the nuances of feeding practices and styles. The assessment of food parenting practice exposures and feeding styles within the literature is often at 1 time point and categorical, yet caregivers may often use several practices and vary among styles depending on the context, child, or specific situation.
- Identify supportive approaches to feeding young children. The role of autonomy supportive practices in the development of young children’s eating behaviors and GBCO outcomes, for instance, is not well characterized.
- Examine GBCO outcomes using more proximal measures of eating behaviors and/or dietary intake. Child GBCO outcomes are distal to the intended target of caregiver feeding styles and practices— namely children’s eating behaviors and intake.
- Examine the potential moderating role of culture, context, and environments on the influence of food parenting on children’s eating behaviors. Research to understand the drivers and interpretation of various approaches to caregiving is critical for identifying strategies to support caregivers in raising children that are responsive to culture, context, environment.
- Examine the potential moderating role of differences among children in food motivated and food avoidant behaviors. Conduct research taking into account children’s predispositions towards eating to move beyond a 1 size fits all approach.

Table 10 Evidence examining the relationship between structured feeding practices (monitoring) and growth, body composition and risk of obesity ^a^,^b^

Study and Population Characteristics | Intervention/Exposure and Comparator, Outcome | Significant Results | Non-Significant Results | Confounders, Model Adjustments, Funding
Hughes, 2021^11^; PCS, U.S.; Analytic N=119; Power Analysis: Power analysis [n=187 with 95% power to detect an effect size of 0.15 for 5 predictor variables]; [underlined: Caregiver Characteristics]; - Mothers: 100%; - Age: 31.45 (6.60) y; - SEP and/or Education: Head start: 100%; Less than high school diploma: 38.3%, High school diploma or equivalent: 24.2%, Some college or more: 37.5%; Currently employed: 21.1%; - Race and/or Ethnicity: Hispanic: 100%; White: 71.9%, American Indian or Alaskan Native: 12.5%, Other (usually indicating Hispanic, Latina, or Mexican): 12.5%, Black or African American: 0.8%; - BMI: NR; - Other: Married: 59.4%, Widowed, separated, divorced: 26.5%, Never married: 14.1%; Parent immigrant status: Born in Mexico: 63.3%, Born in the U.S.: 18.0%, Born in Central America: 17.9%, Born in Cuba: 0.8%; Child born in the U.S.: 96.9%; [underlined: Child Characteristics]; - Female: 53%; - Baseline anthropometry: BMI categories at 4–5 y: Healthy (<85th percentile): 50.0%, Overweight (85th-<95th percentile): 22.7%, Obese (≥95th percentile): 27.3%; - Milk feeding practices: NR; [underlined: Primary aim:] To examine whether or not parental feeding styles at ages 4–5 continued to predict children's weight status at this later time point (7–9 y). To examine the direction of effects between parental feeding styles and child weight status. | [underlined: Exposures and Comparators:] Restriction, Pressure to eat, Monitoring (Continuous); [underlined: CFP Definition:] per CFQ; [underlined: CFP Assessment Method:] Child Feeding Questionnaire (CFQ); [underlined: Child age at initial exposure measurement:] 4–5 [Mean (SD): 4.73 (0.46)] y; [underlined: Outcome(s):] Growth; [underlined: Outcome assessment method]: Weight and height measured by trained staff. Age- and sex-specific BMI standardized scores calculated based on CDC reference standards.; [underlined: Age(s) at outcome assessment:] 7–9 y [Mean (SD): 8.31 (0.72)] | [underlined: BMIz @ 7–9 y, β]; [underlined: Monitoring]: −0.149, p<0.01 | [underlined: BMIz @ 7–9 y, β]; Pressure to eat: 0.076, NS; Restriction: 0.071, NS | [underlined: Key confounders accounted for:] SEP and/or parental or caregiver education; race and/or ethnicity; child's anthropometry at baseline; child sex; [underlined: Key confounders NOT accounted for:] Parental or caregiver BMI; [underlined: Model adjustments:] Baseline BMI z-score, child gender, child age, parental acculturation, child eating behaviors (food responsiveness, emotional overeating, satiety responsiveness), parental feeding practices (parental feeding styles only), parental feeding styles (parental feeding practices only); [underlined: Funding:] NICHD; USDA Children's Nutrition Research Center
Power, 2021^15^; PCS, None, U.S.; Analytic N=129; Power Analysis: NR; [underlined: Caregiver Characteristics]; - Mothers: ~98%, Grandmothers: ~2% Age: 31.5 (6.6) y; - SEP and/or Education: Education of parent: 8th grade or less: 28.7%, Some high school: 9.3%, High school diploma or GED: 24.0%, Some college or technical school: 31.0%,; - Four-year college graduate: 7.0%; Currently employed: 21.7%; - Race and/or Ethnicity: Latina: 100% BMI: Maternal BMI: Healthy (<25): 16.4%, Overweight (≥25 and <30): 30.5%, Obese (≥30): 53.1%; - Other: Marital status: Married: 59.7%, Never married: 27.2%, Widowed, separated, divorced: 13.2%; Parent immigration status: Born in U.S.: 17.7%, Born in Mexico: 63.3%, Born in Central America: 17.9%, Born in another country: 0.8%; Spanish speaking: 79.1%, English speaking: 20.9%; [underlined: Child Characteristics]; - Female: 47%; - Baseline anthropometry: Healthy (<85th percentile): 50.4%, Overweight (85th to <95th percentile): 22.5%, Obese (≥95th percentile): 27.1%. NR differences between groups; - Milk feeding practices: NR; [underlined: Primary aim:] To examine longitudinally, over a 3.5-year period, the relationships between feeding practices, feeding styles, and young children's BMI z-scores, using both self-report and observational measures of maternal feeding. | [underlined: Exposures and Comparators:] Restriction, Pressure to eat, Monitoring (Continuous); [underlined: CFP Definition:] per CFQ; [underlined: CFP Assessment Method:] Child Feeding Questionnaire (CFQ); [underlined: Child age at initial exposure measurement:] 4–5 [Mean (SD): 56.8 (5.5)] mo; [underlined: Outcome(s):] Growth; [underlined: Outcome assessment method:] Height and weight measured by trained staff. Age- and sex-specific BMIZ were calculated based on revised 2000 growth charts from CDC; [underlined: Age(s) at outcome assessment]: 7–9 y | [underlined: BMIz @ 7–9 y, β (SE)]; [underlined: Monitoring:] −0.15 (0.07), p<0.05 | [underlined: BMIz @ 7–9 y, β (SE)]; Restriction: −0.01 (0.08), p≥0.05; Pressure to eat: 0.01 (0.07), p≥0.05; Encourage eating: 11.46 (5.82), p=0.05 | [underlined: Key confounders accounted for:] Race and/or ethnicity; child's anthropometry at baseline; [underlined: Key confounders NOT accounted for:] SEP and/or parental or caregiver education; child sex; parental or caregiver BMI; [underlined: Model adjustments:] Child's baseline BMI; [underlined: Funding:] NICHD; USDA/ARS
Hughes, 2016^10^; PCS, US; Analytic N=129; Power Analysis: NR; [underlined: Caregiver Characteristics]; - Mothers: 100%; - Age: 32.01 (6.68) y; - SEP and/or Education: High school diploma or less: 62.8%, Some college or more: 37.2%, Currently employed: 24.0%; Married: 55.8%, never married: 13.2%, widowed, separated, divorced: 31%; - Race and/or Ethnicity: Latina: 100% BMI: NR; - Other: Parent immigrant status: born in US: 15.5%, born in Mexico: 64.3%, born in Central America: 20.2%; [underlined: Child Characteristics]; - Female: 45%; - Baseline anthropometry: Normal weight: 48.8%, Overweight: 21.7%, Obese: 29.5%, NR differences bw groups; - Milk feeding practices: NR; [underlined: Primary aim:] To investigate the influence of feeding styles and food parenting practices on low-income children's weight status over time | [underlined: Exposures and Comparators:] Restriction, Pressure to eat, Monitoring (Continuous); [underlined: CFP Definition:] per CFQ; [underlined: CFP Assessment Method:] Child Feeding Questionnaire (CFQ); [underlined: Child age at initial exposure measurement:] 3–5 y; [underlined: Outcome(s):] Growth; [underlined: Outcome assessment method:] Weight and height were measured by trained staff members. CDC reference standards were used to generate age- and gender-specific BMI z-scores; [underlined: Age(s) at outcome assessment:] 6 y | [underlined: BMIz @ 6 y, β]; [underlined: Monitoring:] −0.068, p<0.05; Restriction: 0.082, p<0.05 | [underlined: BMIz @ 6 y, β]; Pressure to eat: 0.038, p>0.05 | [underlined: Key confounders accounted for:] race and/or ethnicity; child's anthropometry at baseline; child sex; [underlined: Key confounders NOT accounted for:] SEP and/or parental or caregiver education; parental BMI; [underlined: Model adjustments:] Child sex, child age in months, child BMIz at baseline, acculturation (English domain), parent born in US, food responsiveness, emotional overeating, satiety responsiveness; [underlined: Funding]: NICHD, USDA-ARS
Gubbels, 2011^8^; PCS, KOALA Birth Cohort Study, Netherlands; Analytic N=1513; Power Analysis: NR; [underlined: Caregiver Characteristics]; - Female: NR; - Age: Maternal age at birth: 32.2 (3.7); - SEP and/or Education: Educational level Mothers: High: 54.1%, Medium: 38.0%, Low: 7.9%; Fathers: High: 53.2%, Medium: 33.9%, Low: 12.9%; Average h worked per wk: Mothers: 18.0 (11.1) h/wk, Fathers: 37.8 (10.1) h/wk; - Race and/or Ethnicity: Country of birth: Mother: Netherlands: 97.0%, Other: 3%; Fathers: Netherlands: 96.3%, Other: 3.7%; - BMI: Maternal BMI: 24.0 (3.8), Paternal BMI: 25.0 (3.1); - Other: NA; [underlined: Child Characteristics]; - Female: 49%; - Baseline anthropometry: BMIz @ 5 y: −0.27 (0.99); Restriction: p<0.001, Stimulation healthy intake: p<0.07; - Milk feeding practices: NR; [underlined: Primary aim:] To examine parental and child associates of energy-balanced related parenting practices; to examine the association between energy balance-related parenting and activity behavior and dietary intake in 5-year-old children, and well as the prospective influence on children's BMI development up to age 7 (green arrows); to examine whether child background characteristics moderated the impact of the parenting practice. | [underlined: Exposures and Comparators:] Restriction of unhealthy intake, Monitoring, Stimulation healthy intake (Continuous); [underlined: CFP Definition:] Per CFQ; Stimulation healthy intake assessed using items "I make sure that my child eats enough healthy food products" and "I get my child enthusiastic about healthy products, such as vegetables, fruit, and whole meal products"; [underlined: CFP Assessment Method:] Child Feeding Questionnaire (CFQ)-modified; [underlined: Child age at initial exposure measurement:] 5 y); [underlined: Outcome(s):] Growth; [underlined: Outcome assessment method:] Child's height and weight were reported by parents and used to calculated BMI. BMI z-scores were calculated using the 1997 national reference population (i.e., the Fourth Dutch National Growth Study). Underweight @ 5 y defined as BMIz <5th percentile.; [underlined: Age(s) at outcome assessment:] 7 y | [underlined: Full sample (N= 1513)]; [underlined: BMIz @ 7 y, β]; Stimulation healthy intake: −0.06, p<0.05; [underlined: Sample excluding underweight children @ 5 (N= 1326)]; [underlined: BMIz @ 7 y, β]; Stimulation healthy intake: −0.07, p<0.05 | [underlined: Full sample (N=1513) BMIz @ 7 y, β]; [underlined: Monitoring:] 0.02, p>0.05; Restriction: 0.01, p>0.05; [underlined: Sample excluding underweight children @ 5 (N= 1326)]; [underlined: BMIz @ 7 y, β]; [underlined: Monitoring:] 0.03, p>0.05; Restriction: 0.01, p>0.05 | [underlined: Key confounders accounted for:] SEP and/or parental or caregiver education; race and/or ethnicity; child's anthropometry at baseline; child sex; parental or caregiver BMI; [underlined: Key confounders NOT accounted for:] none; [underlined: Model adjustments:] Child gender, birth weight, BMIz @ 5 y, activity style, hungry eating style, picky eating style, parental BMI, employment, educational level, country of birth, and maternal age.; [underlined: Funding:] Dutch Ministry of Economic Affairs. Dutch Ministry of Health, Welfare and Sports, FrieslandCampina, and the Dutch Sugar Bureau
Afonso, 2016^1^; PCS, Generation XXI, Portugal; Analytic N=4643; Power Analysis: NR; [underlined: Caregiver Characteristics]; - Mothers: 100%; - Age: 34.4 (5.11) y; - SEP and/or Education: Years of schooling: 11.5 (4.21) y; - Race and/or Ethnicity: NR; - BMI: 26.3 (5.04); - Other: NA; [underlined: Child Characteristics]; - Female: 49%; - Baseline anthropometry: BMI @ 4 y: 16.2 (1.73), BMIz @ 4 y: 0.6 (1.08), NR differences bw groups; - Milk feeding practices: NR; [underlined: Primary aim:] To examine bidirectional associations between parental child-feeding practices and BMI at 4 and 7 y | [underlined: Exposures and Comparators:] Restriction, pressure to eat, monitoring, overt control, covert control (Continuous); [underlined: CFP Definition:] Per CFQ; Overt control: represented by a firm attitude from parents about what, how much, where, and when the child eats, which can be perceived by the child; Covert control: child is unable to detect the control; for example avoiding buying energy-dense foods); [underlined: CFP Assessment Method:] Child Feeding Questionnaire (CFQ); Overt and Covert Control Scale; [underlined: Child age at initial exposure measurement:] 4. y; [underlined: Outcome(s):] Growth; [underlined: Outcome assessment method]: Child weight and height were measured by trained staff and used to calculate BMI. BMI was converted age- and sex-specific BMI SD score (BMIz) according to WHO Growth References.; [underlined: Age(s) at outcome assessment]: 7 y | [underlined: BMIz @ 7 y, β (95% CI)]; Pressure to eat: −0.05 (−0.08, −0.03), p<0.05; Overt control: −0.05 (−0.09, −0.01), p<0.05 | [underlined: BMIz @ 7 y, β (95% CI)]; Covert control: −0.02 (−0.04, 0.01), p>0.05; [underlined: Monitoring:] −0.01(−0.04, 0.02), p>0.05; Restriction: 0.02 (−0.01, 0.05), p>0.05 | [underlined: Key confounders accounted for:] SEP and/or parental or caregiver education; child's anthropometry at baseline; child sex; parental or caregiver BMI; [underlined: Key confounders NOT accounted for:] race/ethnicity; [underlined: Model adjustments:] child's sex, mother's age, educational level, maternal BMI, child BMIz at baseline; [underlined: Funding:] Health XXI Operational Programme, III Community Support Framework and North Regional Health Administration, European Regional Development Fund, Operational Competitiveness Program, Portuguese Foundation for Science and Technology Portuguese Ministry of Education and Science, Calouste Gulbenkian Foundation
Rodgers, 2013^17^; PCS, Australia; Analytic N=323; Power Analysis: NR; [underlined: Caregiver Characteristics]; - Mother: 100%; - Age: 35 (0.37) y; - SEP and/or Education: Maternal education: University course completed: 73.7%, Some additional training: 9.0%, Secondary school completed: 11.8%, Some secondary school: 5.0%; Income: <$20,000: 2.7%, $20,000–$60,000: 22.5%, $61,000–$100,000:37.0%, $101,000–$140,000: 18.0%, >$140,000: 19.8%; - Race and/or Ethnicity: NR; - BMI: Maternal BMI: 24.21 (4.66); - Other: NA; [underlined: Child Characteristics]; - Female: NR; - Baseline anthropometry: BMIz @ 2 y: 0.30; NR differences bw groups; - Milk feeding practices: NR; [underlined: Primary aim]: To explore prospective relationships between maternal feeding practice, child weight gain and obesogenic behaviors in 2-year-old children. | [underlined: Exposures and Comparators:] Instrumental feeding, Encouragement, Emotional feeding, Control, Covert control, Monitoring, Pushing to eat more, Fat restriction, Weight restriction (Continuous); [underlined: CFP Definition:] Maternal feeding practice components derived using principal component analysis with 78 maternal feeding practice items from the Child Feeding Questionnaire (CFQ), Preschooler Feeding Questionnaire (PFQ), Parent Feeding Style Questionnaire (PFSQ), Control over Eating Questionnaire (COEQ), and Comprehensive Feeding Practices Questionnaire (CFPQ).; [underlined: CFP Assessment Method:] Child Feeding Questionnaire (CFQ), Preschooler Feeding Questionnaire (PFQ), Parent Feeding Style Questionnaire (PFSQ), Control over Eating Questionnaire (COEQ), Comprehensive Feeding Practices Questionnaire (CFPQ); [underlined: Child age at initial exposure measurement:] 1.5–2.5 [Mean (SD): 2.03 (0.37)] y; [underlined: Outcome(s):] Growth; [underlined: Outcome assessment method:] At baseline, all children had weight and height measured by researchers. At follow-up, children's weight and height were measured by researchers (64.1%) or obtained from health records or parent report (35.9%). Height and weight were used to calculate BMI which were converted to age- and gender-adjusted BMIz.; [underlined: Age(s) at outcome assessment:] 3 y | [underlined: BMIz change 2–3 y, pearson product-moment correlation]; Instrumental feeding: 0.19, p<0.01 | [underlined: BMIz change 2–3 y, pearson product-moment correlation]; Covert control: −0.03, p≥0.05; [underlined: Monitoring:] 0.02, p≥0.05; Pushing to eat more: 0.00, p≥0.05; Encouragement: 0.01, p≥0.05; Emotional feeding: −0.04, p≥0.05; Control: −0.08, p≥0.05; Fat restriction: −0.01, p≥0.05; Weight restriction: −0.08, p≥0.05 | [underlined: Key confounders accounted for:] Child anthropometry at baseline; [underlined: Key confounders NOT accounted for:] SEP and/or parental or caregiver education; race and/or ethnicity; ; child sex; parental or caregiver BMI; [underlined: Model adjustments:] none; [underlined: Funding:] National Heart Foundation Australia
Eichler, 2019^4^; PCS, Leipzig Research Center for Civilization; Diseases (LIFE) Child Study, Germany; Analytic N=1,512 (n=299 to 416 at any time point); Power Analysis: Power analysis [n=299–416 per group with a=0.05 to detect medium (Cohen's d=0.5) or large (Cohen's d=0.8) effect]; [underlined: Caregiver Characteristics]; - Parents: 100%; - Age: NR; - SEP and/or Education: SES: Low: ~7%, Medium: ~47%, High: ~46%; - Race and/or Ethnicity: NR; - BMI: NR; - Other: NR; [underlined: Child Characteristics]; - Female: ~47%; - Baseline anthropometry: BMIz: Underweight: ~1%, Normal weight: ~89%, Overweight: ~5%, Obesity: ~4%; BMIz: ~0.22; - Milk feeding practices: NR; [underlined: Primary aim:] To determine the stability and continuity of parental feeding practices and child zBMI, and their bi-directional associations in a large longitudinal population-based sample of 2- to 12-year-old German children. | [underlined: Exposures and Comparators:] Restrictive feeding, Food as reward, Pressure to eat, Monitoring (Continuous); [underlined: CFP Definition:] Per CFQ; [underlined: CFP Assessment Method:] Child Feeding Questionnaire (CFQ); [underlined: Child age at initial exposure measurement:] 2–3, 3–4, 4–5, 5–6, 6–7, 7–8, 8–9, 9–10, 10–11 y; [underlined: Outcome(s):] Growth; [underlined: Outcome assessment method:] Height and weight measured by research staff. Sex- and age-specific BMI z-scores based on Kromeyer-Hauschild (2002) reference; [underlined: Age(s) at outcome assessment:] 3, 4, 5, 6, 7, 8, 9, 10, 11, 12 y | [underlined: BMIz @ 6, 11 y, β]; [underlined: Monitoring @ 5 y] on BMI @ 6 y: 0.050, p=0.033 | BMIz @ 3, 4, 5, 6, 7, 8, 9, 10, 11, 12 y; [underlined: Monitoring @ 2, 3, 4, 6y on BMI after 1-y follow-up:] Data NR, NS; Food as reward @ 2, 3, 4, 5, 6, y on BMI after 1-y follow-up: Data NR, NS; Pressure to eat @ 2, 3, 4, 5, 6y on BMI after 1-y follow-up: Data NR, NS; Restriction @ 2, 3, 4, 5, 6y on BMI after 1-y follow-up: Data NR, NS | [underlined: Key confounders accounted for:] SEP and/or parental or caregiver education; child sex; [underlined: Key confounders NOT accounted for:] Race and/or ethnicity; child's anthropometry at baseline; parental or caregiver BMI; [underlined: Model adjustments:] Child sex, SES, parenting feeding practices @ baseline and 1 y follow up, BMIz @ baseline and 1 y follow-up; [underlined: Funding:] Leipzig Research Centre for Civilization Diseases; Integrated Research and Treatment Center Adiposity Diseases of Leipzig University; European Union; European Regional Development Fund; Free State of Saxony.
Souto-Gallardo, 2020^18^; PCS, Juega, Mexico; Analytic N=91; Power Analysis: NR; [underlined: Caregiver Characteristics]; - Mothers: 98.1%; - Age: 31.7 (7.1) y; - SEP and/or Education: Less than high school: 35.2%, High school: 18.7%, College: 46.2%; Family income per mo: ≤$265/mo: 37.8%, $265−530/mo: 37.8%, >$530/mo: 24.4%; - Race and/or Ethnicity: Mexican: 100%; - BMI: BMI: 29.1 (6.4); Normal weight: 25.3%, Overweight: 37.4%, Obesity: 37.4%; WC (Mean (25th, 75th percentile): 94.0 (82, 103); WC (% > 90th percentile): 77.5%; - Other: NA; [underlined: Child Characteristics]; - Female: 52%; - Baseline anthropometry:; BMIZ at baseline (Mean, 25th, 75th percentile): 1.2 (0.4, 1.5); Baseline weight status: Underweight (≤2.0 SD): 0.0%, Normal weight: (−1.99 SD ≤ 1.0 SD) 50.0%, High risk of overweight (>1.0 SD ≤ 2.0 SD): 36.5%, Overweight (>2.0 SD ≤ 3.0 SD): 5.4%,Obesity (>3.0 SD): 8.1%; WC (% ≥90th percentile): 54.0%, Mean (25th, 75th percentile):; - Milk feeding practices: NR; [underlined: Primary aim:] To evaluate the association between food parenting practices and weight status (BMIz and waist circumference [WC]) among Mexican preschoolers and the directionality of this association after 12 months of follow-up. | [underlined: Exposures and Comparators:] Food as reward, Restriction, Monitoring, Perceived responsibility for child feeding, Pressure to eat (Continuous); [underlined: CFP Definition:] Per CFQ; [underlined: CFP Assessment Method:] Child Feeding Questionnaire (CFQ); [underlined: Child age at initial exposure measurement:] 2–5 y (Mean (SD): (3.8 (0.6) y); [underlined: Outcome(s):] Growth, Body composition; [underlined: Outcome assessment method]: Height, weight, waist circumference measured by trained staff. Sex- and age-adjusted BMI z-scores calculated using WHO standard. Waist circumference (WC) compared with the 90th percentile of the Third National Health and Nutrition Examination Survey of Mexican American children.; [underlined: Age(s) at outcome assessment:] 3–6 y | [underlined: Change in BMIz from 2–5 y and 3–6 y, β]; [underlined: Girls]; Food reward: 0.306 p=0.04 Restriction: 0.337 p=0.03 | [underlined: BMIz @ 3–6 y, β]; [underlined: Monitoring:] −0.085, p=0.44; Food reward: −0.011, p=0.86; Pressure to eat: −0.019, p=0.86; Restriction: −0.108, p=0.31; Boys; [underlined: Monitoring:] −0.241, p=0.17; Food reward: −0.018, p=0.89; Pressure to eat: 0.022, p=0.88; Restriction: −0.019, p=0.90; Girls; [underlined: Monitoring:] 0.130, p=0.39; Food reward: −0.208, p=0.16; Pressure to eat: −0.063, p=0.68; Restriction: −0.103, p=0.49; [underlined: Change in BMI from 2–5 y and 3–6 y, β]; [underlined: Monitoring:] 0.046, p=0.68; Food reward: 0.204, p=0.06; Pressure to eat: 0.039, p=0.71; Restriction: −0.129, p=0.32; Boys; [underlined: Monitoring:] −0.066, p=0.95; Food reward: 0.235, p=0.15; Pressure to eat: 0.078, p=0.62; Restriction: 0.011, p=0.95; Girls; [underlined: Monitoring:] 0.136, p=0.37; Pressure to eat: −0.002, p=0.99; [underlined: Change in WC from 2–5 y and 3–6 y, β]; [underlined: Monitoring:] 0.083, p=0.45; Food reward: 0.087, p=0.41; Pressure to eat: 0.003, p=0.98; Restriction: −0.005, p=0.48; Boys; [underlined: Monitoring:] 0.181, p=0.31; Food reward: 0.026, p=0.87; Pressure to eat: −0.017, p=0.91; Restriction: −0.017, p=0.92; Girls; [underlined: Monitoring:] 0.078, p=0.61; Food reward: 0.182, p=0.22; Pressure to eat: 0.005, p=0.98; Restriction: −0.178, p=0.23 | [underlined: Key confounders accounted for:] Race and/or ethnicity; child sex; [underlined: Key confounders NOT accounted for:] SEP and/or parental or caregiver education; child's anthropometry at baseline; parental or caregiver BMI; [underlined: Model adjustments:] Other feeding practices; [underlined: Funding]: NR
Papaioannou, 2023^14^; PCS, US; Analytic N=129; Power Analysis: NR; [underlined: Caregiver Characteristics]; - Mothers: 100%; - Age: 31.55 (6.60) y; - SEP and/or Education: > High school: 38%, High school or equivalent: 24%, Some college or more: 38%; Employed: 20.9%; Attending HeadStart: 100%; - Race and/or Ethnicity: Hispanic: 100%; - BMI: NR; - Other: Parent Married: 58.9%, Never married: 14%, widowed/separated/divorced: 27.1%; Parent born in US: 17.8%, Born in Mexico: 63.5%, Born in Central America: 17.9%; Child: Born in U.S: 96.9%; [underlined: Child Characteristics]; - Female: 54%; - Baseline anthropometry: Underweight (<5th percentile): 1.6, Healthy weight (5th to <85th percentile): 48.8% Overweight (85th to <95th percentile): 22.5% Obese (≥95th percentile): 27.1%; Pressure to eat: p<0.001, Authoritarian: p<0.05, Indulgent: p<0.05; - Milk feeding practices: NR; [underlined: Primary aim:] To examine the degree to which individual differences in children’s food motivation in the preschool years interacted with mothers’ feeding styles in predicting subsequent weight status in Hispanic children from low-income levels. | [underlined: Exposures and Comparators:] Restriction, Pressure to eat, Monitoring (Continuous); [underlined: CFP Definition:] Per CFQ; [underlined: CFP Assessment Method:] Child Feeding Questionnaire (CFQ); [underlined: Child age at initial exposure measurement:] 4–5 y [Mean (SD): 4.76 (0.46)] y; [underlined: Outcome(s):] Growth; [underlined: Outcome assessment method:] Height and weight were measured by trained staff. Age- and gender-specific BMIz were calculated using the CDC Reference Standards.; [underlined: Age(s) at outcome assessment:] 8.34 (0.71) y | [underlined: BMIz @ ~ 8 y, β (95% CI)]; [underlined: Monitoring:] −0.17 (−0.30, −0.04), p<0.01 | [underlined: BMIz @ ~ 8 y, β (95% CI)]; Pressure to eat: 0.02 (−0.11, 0.15), p≥0.05; Restriction: 0.15 (−0.02, 0.32), p≥0.05 | [underlined: Key confounders accounted for:] Race and/or ethnicity, SEP and/or parental or caregiver education, child's anthropometry at baseline; [underlined: Key confounders NOT accounted for:] Parental or caregiver BMI; [underlined: Model adjustments]: Child BMIZ @ time 1, CFQ feeding practices, CFSQ feeding styles, highly motivated eating score, 3 feeding styles by highly motivated eating interactions; [underlined: Funding:] NICHD, USDA/ARS
Quah, 2019^16^; PCS, the Growing Up in Singapore Toward healthy Outcomes (GUSTO), Singapore; Analytic N=428; Power Analysis: NR; [underlined: Caregiver Characteristics]; - Mothers: 100%; - Age: 30.6 (5.3) y; - SEP and/or Education: None/primary/secondary: 28%, post−secondary/tertiary: 72%; - Race and/or Ethnicity: Child Ethnicity: Chinese: 47%, Malay: 32%, Indian: 21%; - BMI: BMI @ 15 wk gestation: 24.1 (5.0); - Other: Primiparous: 44%, Multiparous: 56%; [underlined: Child Characteristics]; - Female: 49%; - Baseline anthropometry: BMIz @ 4 y: 0.22 (1.3); Overweight status (> + 2 z-score) @ 4 y: 7.8%; Normal weight: 92.2%; NR differences bw groups; - Milk feeding practices: Never BF: 3.6%, BF for <6mo: 86.4%, BF for >6 mo: 10%; [underlined: Primary aim:] To examine bidirectional associations between the 12 different maternal feeding practices (measured at 5 y) subscales and child BMI (measured at 4 and 6y) and to test the strength of bidirectional associations for feeding practices that are significantly associated with BMI. | [underlined: Exposures and Comparators:] Encouraging balance/variety, Healthy environment, Teaching about nutrition, Child involvement, Monitoring, Restriction for weight control, Restriction for health, Pressure, Emotional regulation, Child control, Food as reward (Continuous); [underlined: CFP Definition:] Per CFPQ; [underlined: CFP Assessment Method]: Comprehensive Feeding Practices Questionnaire (CFPQ); [underlined: Child age at initial exposure measurement:] 4.9 (0.2) y; [underlined: Outcome(s):] Growth; [underlined: Outcome assessment method:] Child’s weights and heights were measured by trained staff and used to calculated BMI. Age and sex-adjusted BMIz were calculated using the WHO Child Growth Standards 2007 in the WHO Anthro software. Child overweight/obese were categorized using WHO cut-offs of above +2 z-score for children aged 4, and +1 z-score for children aged 6 years.; [underlined: Age(s) at outcome assessment:] 6 y | [underlined: BMIz @ 6 y, β (95% CI)]; Restriction for weight control: 0.02 (0.002, 0.03), p=0.024 | [underlined: BMIz @ 6 y, β (95% CI)]; Modelling: −0.02 (−0.06, 0.02), p=0.351; Encouraging balance and variety: −0.05 (−0.10, 0.003), p=0.048; Healthy environment: 0.02 (−0.03, 0.07), p=0.419; [underlined: Monitoring:] 0.05 (0.009, 0.08), p= 0.013; Teaching about nutrition: −0.02 (−0.08, 0.04), p=0.320; Child involvement: −0.05 (−0.11,−0.001), p= 0.045; Restriction for health: 0.056 (0.005, 0.11), p=0.030; Emotional regulation: 0.007 (−0.05, 0.06), p=0.811; Child control: −0.02 (−0.07, 0.02), p=0.252; Food as reward: −0.01 (−0.07, 0.05), p=0.690; Pressure: 0.01 (−0.01, 0.03), p=0.300 | [underlined: Key confounders accounted for:] SEP and/or parental or caregiver education; race and/or ethnicity; child's anthropometry at baseline; child sex; parental or caregiver BMI; [underlined: Key confounders NOT accounted for]: None; [underlined: Model adjustments]: CFPQ assessment, BMI during early pregnancy (<14 weeks), child birth order, duration of breastfeeding, ethnicity, and maternal education, BMIz at 5 y (model with restriction for weight control and pressure only); [underlined: Funding]: Singapore National Research Foundation, Translational and Clinical Research (TCR) Flagship Programme; Singapore Institute for Clinical Sciences; Agency for Science, Technology and Research (A∗STAR), Singapore; the Singapore Institute for Clinical Sciences, A∗STARand Nestec.
Bergmeier, 2014^3^; PCS, Australia; Analytic N=201; Power Analysis: NR; [underlined: Caregiver Characteristics]; - Mothers: 100%; - Age: 36.11 (4.09) y; - SEP and/or Education: Bachelor's degree: 67.7%; Family income <A$45,000: 6.4%, A$45,001-A$85,000: 31.5%, A$85,001−A$145,000: 44.5%, > A$145,001: 17.6%; - Race and/or Ethnicity: NR; - BMI: Maternal BMI: 25.03 (4.54); Underweight; 1.9%, normal weight: 52.9%, overweight: 35.2%, obese: 10%; - Other: Born in Australia: 81.9%, Europe: 8.9%, New Zealand: 3.4%; [underlined: Child Characteristics]; - Female: 58%; - Baseline anthropometry: Underweight: 16%, Healthy weight: 71%, Overweight: 10%, Obese: 3%; NR differences bw groups; - Milk feeding practices: NR; [underlined: Primary aim:] To examine cross-sectional and prospective associations between child temperament, maternal feeding, maternal parenting styles, mother–child interaction, preschoolers’ eating behaviors and BMI | [underlined: Exposures and Comparators:] Restriction, pressure to eat, monitoring (Continuous); [underlined: CFP Definition:] Per CFQ; [underlined: CFP Assessment Method:] Child Feeding; Questionnaire (CFQ); [underlined: Child age at initial exposure measurement:] 2–5 [Mean (SD): 2.92 (0.75)] y; [underlined: Outcome(s):] Growth; [underlined: Outcome assessment method:] Mothers reported child’s height and weight measurements. BMI z-scores were calculated. BMI cut-off points developed by CDC were used to classify children as normal weight, overweight or obese.; [underlined: Age(s) at outcome assessment]: ~ 4 y | | [underlined: BMIz @ ~4y, β]; [underlined: Monitoring:] −0.01, NS; Restriction: 0.01, NS; Pressure to eat: 0.02, NS | [underlined: Key confounders accounted for:] SEP and/or parental or caregiver education; parental or caregiver BMI; [underlined: Key confounders NOT accounted for:] Race and/or ethnicity; child's anthropometry at baseline; child sex; [underlined: Model adjustments:] Maternal educational achievement, family income, and maternal BMI, child BMIZ,; [underlined: Funding:] Australian Research Council Discovery
Faith, 2004^5^; PCS, Infant Growth Study, US; Analytic N=57; Power Analysis: Underpowered to detect weak associations (r=0.1–0.2); [underlined: Caregiver Characteristics]; - Mothers: 88%, Fathers: 12%; - Age: NR; - SEP and/or Education: NR; - Race and/or Ethnicity: White: 100%; - BMI: Mother's BMI (high risk): 30.3 (4.2), Mother's BMI (low risk): 19.5 (1.1), Father's BMI (high risk): 27.6 (5.9), Father's BMI (low risk): 27.9 (2.9); - Other: NA; [underlined: Child Characteristics]; - Female: NR; - Baseline anthropometry: BMIz @ 5 y: 0.30 (1.2), Monitoring (Low Risk): p<0.05; - Milk feeding practices: NR; [underlined: Primary aim:] To examine whether 1) Parental feeding attitudes and styles stable for 2 years, 2) Parental feeding attitudes and styles associated with child BMI z scores cross-sectionally and prospectively, and whether these associations depend on child obesity risk status, and 3) Parental feeding attitudes and styles predict subsequent child BMI z scores, when controlling for the child’s prior BMI z score | [underlined: Exposures and Comparators]: Pressure to eat, Restriction, Monitoring (Continuous); [underlined: CFP Definition]: Per CFQ; [underlined: CFP Assessment Method]: Child Feeding Questionnaire (CFQ); [underlined: Child age at initial exposure measurement]: 5 y; [underlined: Outcome(s):] Growth; [underlined: Outcome assessment method]: Child weight and height was measured, and BMI was computed and converted to z scores.; [underlined: Age(s) at outcome assessment]: 7 y | [underlined: BMIz @ 7 y, β]; [underlined: Monitoring (low risk):] −0.33, p≤0.05; Restriction (high risk): 0.39, p≤0.05; Pressure to eat (high risk): −0.35, p≤0.05 | [underlined: BMIz @ 7 y, β]; [underlined: Monitoring (high risk):] 0.10, p>0.05; Restriction (low risk): 0.07, p>0.05; Pressure to eat (low risk): −0.11, p>0.05 | [underlined: Key confounders accounted for]: Child's anthropometry at baseline; parental or caregiver BMI, child sex; [underlined: Key confounders NOT accounted for:] SEP and/or parental or caregiver education; race and/or ethnicity; [underlined: Model adjustments:]; Caregiver feeding styles (restriction, monitoring, pressure to eat), Child BMIz @ 3 y; [underlined: Funding]: NIH; General Clinical Research Center; the Nutrition and Growth Laboratory of Children’s Hospital of Philadelphia
Gregory, 2010^7^; PCS, The Child and Family Health Study, Australia; Analytic N=106; Power Analysis: NR; [underlined: Caregiver Characteristics]; - Mothers: 100%; - Age: 35 (5.2) y; - SEP and/or Education: Tertiary education: 60%; - Race and/or Ethnicity: NR; - BMI: Overweight: 51%; - Other: Married/de facto relationship: 87%,; [underlined: Child Characteristics]; - Female: 51%; - Baseline anthropometry: Overweight/obese: 15%; Pressure to eat: p<0.05; - Milk feeding practices: NR; [underlined: Primary aim:] To examine the extent to which maternal feeding practices prospectively predict the development of eating behavior and BMI in preschool-aged children. | [underlined: Exposures and Comparators:] Pressure to eat, Restriction, Monitoring, Modeling (Continuous); [underlined: CFP Definition:] Per CFQ, Modeling of eating healthy foods; [underlined: CFP Assessment Method:] Child Feeding Questionnaire (CFQ), 3-items (modeling); [underlined: Child age at initial exposure measurement:] 2–4 [Mean (SD): 3.3 (0.8)] y; [underlined: Outcome(s):] Growth; [underlined: Outcome assessment method:] Mothers reported on their child's age, gender, weight and height. Child BMI z-scores were calculated per CDC 2000 growth charts; [underlined: Age(s) at outcome assessment]: 4.3 y | | [underlined: BMIz @~4 y, β]; [underlined: Monitoring:] p≥0.05; Modeling: p≥0.05; Pressure to eat: p≥0.05; Restriction: p≥0.05 | [underlined: Key confounders accounted for:] SEP and/or parental or caregiver education; child sex; parental or caregiver BMI, child's anthropometry at baseline; [underlined: Key confounders NOT]; [underlined: accounted for:] Race and/or ethnicity;; [underlined: Model adjustments:] Baseline BMIz, Child age and gender, maternal age, Maternal BMI, education; [underlined: Funding:] National Heart Foundation Australia
Jansen, 2014^12^; PCS, Generation R (fetal life onwards), Netherlands; Analytic N=4166; Power Analysis: NR; [underlined: Caregiver Characteristics]; - Mothers: 100%; - Age: NR; - SEP and/or Education: <3 y of secondary school: 8.2%, Secondary: 26.8%, Higher vocational: 29.7%, Academic: 35.3%; - Race and/or Ethnicity: Dutch: 66.5%, Other Western: 9.8%, Non-Western: 23.7%; - BMI: 24.5 (6 4.1); - Other: NA; [underlined: Child Characteristics]; - Female: 50%; - Baseline anthropometry: BMI SD score @ 2y: 0.22 (1.0), BMI SD score @ 4y: 0.20 (0.87); Restriction & Pressure to eat: p<0.001; - Milk feeding practices: NR; [underlined: Primary aim]: To examine longitudinal relations between selected feeding practices (pressure, restriction, monitoring) and early childhood BMI in a large population-based cohort. | [underlined: Exposures and Comparators:] Pressure to eat, Restriction, Monitoring, Pressuring feeding (Continuous); [underlined: CFP Definition:] Per CFQ, Pressuring feeding if 2y-old child would not eat measured using 5 self-report items; [underlined: CFP Assessment Method:] Child Feeding Questionnaire (CFQ), 5-items (Pressuring feeding); [underlined: Child age at initial exposure measurement:] Pressuring feeding: 2 y, CFQ: 4.1 (0.1) y; [underlined: Outcome(s):] Growth; [underlined: Outcome assessment method:] Children’s weights and heights were measured by trained staff using standardized procedures. BMI was calculated, and age- and sex-specific BMI SD scores were calculated using the Dutch reference population.; [underlined: Age(s) at outcome assessment]: 4, 6 y | [underlined: BMI @ 6 y, β (95% CI)]; Pressure to eat: −0.02 (−0.04, −0.01), p=0.01 | [underlined: BMI SD @ 4 y, β (95% CI)]; Pressuring feeding: −0.01 (−0.04, 0.01), p=0.32; [underlined: BMI SD @ 6 y, β (95% CI)]; [underlined: Monitoring]: −0.01 (−0.04, 0.02), p=0.40; Restriction: 0.01 (−0.01, 0.03), p=0.25 | [underlined: Key confounders accounted]; [underlined: for:] SEP and/or parental or caregiver education; race and/or ethnicity; child's anthropometry at baseline; child sex; parental or caregiver BMI; [underlined: Key confounders NOT accounted for]: None; [underlined: Model adjustments:] Child sex, age at CFQ assessment and national origin, maternal BMI, maternal education, child BMI at baseline (2 y or 4 y); [underlined: Funding:] Nestlé Nutrition (Nestec Ltd), Metagenics Inc
Karp, 2014^13^; PCS, US; Analytic N=77; Power Analysis: NR; [underlined: Caregiver Characteristics]; - Mothers: 93.5%; - Age: 31.6 (5.6) y; - SEP and/or Education: <HS: 65%, ≥HS <College: 30%, ≥College: 5.2%; - Race and/or Ethnicity: Latino: 100%; - BMI: BMI: 29.73 (5.65); - Other: Country of origin: Mexico: 84.4%, Other central American country: 10.4%, US: 5.2%; Acculturation (low): 97.4%; [underlined: Child Characteristics]; - Female: 52%; - Baseline anthropometry: BMI %, median (25th and 75th IQR): 81.9 (51.3, 92.8), NS difference bw groups; - Milk feeding practices: NR; [underlined: Primary aim:] To examine the relationships between parental patterns regarding child feeding and child Body Mass Index (BMI) percentile in Latino parent-preschooler dyads participating in a clinical trial. | [underlined: Exposures and Comparators]: Restriction, Monitoring (Continuous); [underlined: CFP Definition:] Per CFQ; [underlined: CFP Assessment Method:] Child Feeding Questionnaire (CFQ); [underlined: Child age at initial exposure measurement:] 2–6 [Mean (SD): 4.14 (0.87)] y; [underlined: Outcome(s):] Growth; [underlined: Outcome assessment method:] Child BMI was calculated from height and weight measured using a stadiometer and a a calibrated digital scale, respectively. BMI percentile for age and gender was calculated using the CDC calculator and corresponding weight categorization (normal: ≥5% but <85%; overweight: ≥85% but <95%; obese: ≥95%) was assigned.; [underlined: Age(s) at outcome assessment:] ~ 4 y | | [underlined: BMI % 3 mo change, r Change in Monitoring]: 0.10, p=0.400; Change in Restriction: 0.12, p=0.327 | [underlined: Key confounders accounted for:] None; [underlined: Key confounders NOT accounted for:] SEP and/or parental or caregiver education; race and/or ethnicity; child's anthropometry at baseline; child sex; parental or caregiver BMI; [underlined: Model adjustments]: None; [underlined: Funding]: Project Diabetes Implementation, State of Tennessee

a Abbreviations: BMI: Body Mass Index; BMIz: Body Mass Index Z score; CFP: Caregiver feeding practice, CFQ: Child Feeding Questionnaire; NR: Not Reported; NA: Not Applicable; SEP: Socioeconomic position

b Food parenting practices that fall within this bucket are underlined.

Table 11 Risk of bias for observational studies examining structured feeding practices (monitoring) and growth, body composition and risk of obesity^a^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Afonso, 2016^1^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Bergmeier, 2014^3^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | HIGH | SOME CONCERNS | SOME CONCERNS | HIGH
Eichler, 2019^4^ | HIGH | SOME CONCERNS | LOW | LOW | HIGH | LOW | LOW | HIGH
Faith, 2004^5^ | HIGH | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | HIGH
Gregory, 2010^7^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | HIGH | SOME CONCERNS | SOME CONCERNS | HIGH
Gubbels, 2011^8^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | HIGH
Hughes, 2016^10^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Hughes, 2021^11^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Jansen, 2014^12^ | LOW | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Karp, 2014^13^ | VERY HIGH | SOME CONCERNS | LOW | HIGH | LOW | LOW | SOME CONCERNS | VERY HIGH
Papaioannou, 2023^14^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Power, 2021^15^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Quah, 2019^16^ | LOW | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Rodgers, 2013^17^ | VERY HIGH | SOME CONCERNS | LOW | LOW | HIGH | SOME CONCERNS | SOME CONCERNS | VERY HIGH
Souto-Gallardo, 2020^18^ | HIGH | SOME CONCERNS | LOW | LOW | LOW | LOW | LOW | HIGH

a Possible ratings of low, some concerns, high, very high, no information, or not applicable were determined using the "Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)" tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602. ) *Low risk of bias except for concerns about uncontrolled confounding.

Table 12 Evidence examining the relationship between structured feeding practices (other structured feeding practices) and growth, body composition and risk of obesity ^a^,^b^

Study and Population Characteristics | Intervention/Exposure and Comparator, Outcome | Significant Results | Non-Significant Results | Confounders, Model Adjustments, Funding
Afonso, 2016^1^; PCS, Generation XXI, Portugal; Analytic N=4643; Power Analysis: NR; [underlined: Caregiver Characteristics]; - Mothers: 100%; - Age: 34.4 (5.11) y; - SEP and/or Education: Years of schooling: 11.5 (4.21) y; - Race and/or Ethnicity: NR; - BMI: 26.3 (5.04); - Other: NA; [underlined: Child Characteristics]; - Female: 49%; - Baseline anthropometry: BMI @ 4 y: 16.2 (1.73), BMIz @ 4 y: 0.6 (1.08), NR differences bw groups; - Milk feeding practices: NR; [underlined: Primary aim:] To examine bidirectional associations between parental child-feeding practices and BMI at 4 and 7 y | [underlined: Exposures and Comparators:] Restriction, pressure to eat, monitoring, overt control, covert control (Continuous); [underlined: CFP Definition:] Per CFQ; Overt control: represented by a firm attitude from parents about what, how much, where, and when the child eats, which can be perceived by the child; Covert control: child is unable to detect the control; for example avoiding buying energy-dense foods); [underlined: CFP Assessment Method:] Child Feeding Questionnaire (CFQ); Overt and Covert Control Scale; [underlined: Child age at initial exposure measurement:] 4. y; [underlined: Outcome(s):] Growth; [underlined: Outcome assessment method]: Child weight and height were measured by trained staff and used to calculate BMI. BMI was converted age- and sex-specific BMI SD score (BMIz) according to WHO Growth References.; [underlined: Age(s) at outcome assessment]: 7 y | [underlined: BMIz @ 7 y, β (95% CI)]; Pressure to eat: −0.05 (−0.08, −0.03), p<0.05; Overt control: −0.05 (−0.09, −0.01), p<0.05 | [underlined: BMIz @ 7 y, β (95% CI)]; [underlined: Covert control:] −0.02 (−0.04, 0.01), p>0.05; Monitoring: −0.01(−0.04, 0.02), p>0.05; Restriction: 0.02 (−0.01, 0.05), p>0.05 | [underlined: Key confounders accounted for:] SEP and/or parental or caregiver education; child's anthropometry at baseline; child sex; parental or caregiver BMI; [underlined: Key confounders NOT accounted for:] race/ethnicity; [underlined: Model adjustments:] child's sex, mother's age, educational level, maternal BMI, child BMIz at baseline; [underlined: Funding:] Health XXI Operational Programme, III Community Support Framework and North Regional Health Administration, European Regional Development Fund, Operational Competitiveness Program, Portuguese Foundation for Science and Technology Portuguese Ministry of Education and Science, Calouste Gulbenkian Foundation
Rodgers, 2013^17^; PCS, Australia; Analytic N=323; Power Analysis: NR; [underlined: Caregiver Characteristics]; - Mother: 100%; - Age: 35 (0.37) y; - SEP and/or Education: Maternal education: University course completed: 73.7%, Some additional training: 9.0%, Secondary school completed: 11.8%, Some secondary school: 5.0%; Income: <$20,000: 2.7%, $20,000–$60,000: 22.5%, $61,000–$100,000:37.0%, $101,000–$140,000: 18.0%, >$140,000: 19.8%; - Race and/or Ethnicity: NR; - BMI: Maternal BMI: 24.21 (4.66); - Other: NA; [underlined: Child Characteristics]; - Female: NR; - Baseline anthropometry: BMIz @ 2 y: 0.30; NR differences bw groups; - Milk feeding practices: NR; [underlined: Primary aim]: To explore prospective relationships between maternal feeding practice, child weight gain and obesogenic behaviors in 2-year-old children. | [underlined: Exposures and Comparators:] Instrumental feeding, Encouragement, Emotional feeding, Control, Covert control, Monitoring, Pushing to eat more, Fat restriction, Weight restriction (Continuous); [underlined: CFP Definition:] Maternal feeding practice components derived using principal component analysis with 78 maternal feeding practice items from the Child Feeding Questionnaire (CFQ), Preschooler Feeding Questionnaire (PFQ), Parent Feeding Style Questionnaire (PFSQ), Control over Eating Questionnaire (COEQ), and Comprehensive Feeding Practices Questionnaire (CFPQ).; [underlined: CFP Assessment Method:] Child Feeding Questionnaire (CFQ), Preschooler Feeding Questionnaire (PFQ), Parent Feeding Style Questionnaire (PFSQ), Control over Eating Questionnaire (COEQ), Comprehensive Feeding Practices Questionnaire (CFPQ); [underlined: Child age at initial exposure measurement:] 1.5–2.5 [Mean (SD): 2.03 (0.37)] y; [underlined: Outcome(s):] Growth; [underlined: Outcome assessment method:] At baseline, all children had weight and height measured by researchers. At follow-up, children's weight and height were measured by researchers (64.1%) or obtained from health records or parent report (35.9%). Height and weight were used to calculate BMI which were converted to age- and gender-adjusted BMIz.; [underlined: Age(s) at outcome assessment:] 3 y | [underlined: BMIz change 2–3 y, pearson product-moment correlation] Instrumental feeding: 0.19, p<0.01 | [underlined: BMIz change 2–3 y, pearson product-moment correlation Covert control]: −0.03, p≥0.05 Monitoring: 0.02, p≥0.05 Pushing to eat more: 0.00, p≥0.05 Encouragement: 0.01, p≥0.05; Emotional feeding: −0.04, p≥0.05; Control: −0.08, p≥0.05; Fat restriction: −0.01, p≥0.05 Weight restriction: −0.08, p≥0.05 | [underlined: Key confounders accounted for:] Child anthropometry at baseline; [underlined: Key confounders NOT accounted for:] SEP and/or parental or caregiver education; race and/or ethnicity; child sex; parental or caregiver BMI; [underlined: Model adjustments:] none; [underlined: Funding:] National Heart Foundation Australia
Quah, 2019^16^; PCS, the Growing Up in Singapore Toward healthy Outcomes (GUSTO), Singapore; Analytic N=428; Power Analysis: NR; [underlined: Caregiver Characteristics]; - Mothers: 100%; - Age: 30.6 (5.3) y; - SEP and/or Education: None/primary/secondary: 28%, post-secondary/tertiary: 72%; - Race and/or Ethnicity: Child Ethnicity: Chinese: 47%, Malay: 32%, Indian: 21%; - BMI: BMI @ 15 wk gestation: 24.1 (5.0); - Other: Primiparous: 44%, Multiparous: 56%; [underlined: Child Characteristics]; - Female: 49%; - Baseline anthropometry: BMIZ @ 4 y: 0.22 (1.3); Overweight status (> + 2 z-score) @ 4 y: 7.8%; Nornal weight: 92.2%; NR differences bw groups; - Milk feeding practices: Never BF: 3.6%, BF for <6mo: 86.4%, BF for >6 mo: 10%; [underlined: Primary aim:] To examine bidirectional associations between the 12 different maternal feeding practices (measured at 5 y) subscales and child BMI (measured at 4 and 6y) and to test the strength of bidirectional associations for feeding practices that are significantly associated with BMI. | [underlined: Exposures and Comparators:] Encouraging balance/variety, Healthy environment, Teaching about nutrition, Child involvement, Monitoring, Restriction for weight control, Restriction for health, Pressure, Emotional regulation, Child control, Food as reward (Continuous); [underlined: CFP Definition:] Per CFPQ; [underlined: CFP Assessment Method]: Comprehensive Feeding Practices Questionnaire (CFPQ); [underlined: Child age at initial exposure measurement:] 4.9 (0.2) y; [underlined: Outcome(s):] Growth; [underlined: Outcome assessment method:] Child’s weights and heights were measured by trained staff and used to calculated BMI. Age and sex-adjusted BMI z-scores were calculated using the WHO Child Growth Standards 2007 in the WHO Anthro software. Child overweight/obese were categorized using WHO cut-offs of above +2 z-score for children aged 4, and +1 z-score for children aged 6 years.; [underlined: Age(s) at outcome assessment:] 6 y | [underlined: BMIz @ 6 y, β (95% CI)]; Restriction for weight control: 0.02 (0.002, 0.03), p=0.024 | [underlined: BMIz @ 6 y, β (95% CI) Modeling:] −0.02 (−0.06, 0.02), p=0.351; Encouraging balance and variety: −0.05 (−0.10, 0.003), p=0.048; [underlined: Healthy environment:] 0.02 (−0.03, 0.07), p=0.419; Monitoring: 0.05 (0.009, 0.08), p= 0.013; Teaching about nutrition: −0.02 (−0.08, 0.04), p=0.320; Child involvement: −0.05 (−0.11,−0.001), p= 0.045; Restriction for health: 0.056 (0.005, 0.11), p=0.030; Emotional regulation: 0.007 (−0.05, 0.06), p=0.811; Child control: −0.02 (−0.07, 0.02), p=0.252; Food as reward: −0.01 (−0.07, 0.05), p=0.690; Pressure: 0.01 (−0.01, 0.03), p=0.300 | [underlined: Key confounders accounted for:] SEP and/or parental or caregiver education; race and/or ethnicity; child's anthropometry at baseline; child sex; parental or caregiver BMI; [underlined: Key confounders NOT accounted for]: None; [underlined: Model adjustments]: CFPQ assessment, BMI during early pregnancy (<14 weeks), child birth order, duration of breastfeeding, ethnicity, and maternal education, BMIz at 5 y (model with restriction for weight control and pressure only); [underlined: Funding]: Singapore National Research Foundation, Translational and Clinical Research (TCR) Flagship Programme; Singapore Institute for Clinical Sciences; Agency for Science, Technology and Research (A∗STAR), Singapore; the Singapore Institute for Clinical Sciences, A∗STARand Nestec.
Arcan, 2013^2^; PCS, Bright Start, U.S.; Analytic N=424; Power Analysis: NR; [underlined: Caregiver Characteristics]; - Mothers/stepmothers: 67%, Father/stepfather: 9%, Grandmother: 16%, Other: 8%; - Age: 35.6 (10.7) y; - SEP and/or Education: Living on reservation: 100%; - Race and/or Ethnicity: American Indian: 100%; - BMI: 32.5 (7.3); - Other: NA; [underlined: Child Characteristics]; - Female: 49%; - Baseline anthropometry: Overweight/obese: 29%, NS differences bw groups; - Milk feeding practices: NR; [underlined: Primary aim:] To examine cross-sectional and prospective associations between aspects of the home environment (parent report of food availability, child dietary intake frequency, child sedentary behaviors and parent perceived barriers to physical activity) and child BMI among young American Indian children (4–8 years) living on a reservation. | [underlined: Exposures and Comparators:] Food availability (Continuous); [underlined: CFP Definition]: Availability of 47 food and beverage items at home; [underlined: CFP Assessment Method]: The home food/beverage availability questionnaire; [underlined: Child age at initial exposure measurement]: 4.7–7.9 [Mean (SD): 5.8 (0.5)] y; [underlined: Outcome(s):] Weight status; [underlined: Outcome assessment method:] Body weight and height were measured by trained study research staff in schools. Weight status categories were created using sex-specific BMI-for-age percentiles derived from the 2000 growth charts of the CDC (normal weight: BMI < 85th percentile; overweight as BMI ≥ 85th but < 95th percentile; obese: BMI ≥ 95th percentile); [underlined: Age(s) at outcome assessment]: ~ 8 y | | [underlined: Predicted probability of child weight status @ 8 y (normal weight, overweight, obese) Sweet snacks:] p=0.050; [underlined: Probability at mean change]; [underlined: of predictor, %]; [underlined: Normal weight at baseline:] 80.0, 17.3, 2.6; [underlined: Overweight at baseline:] 8.5, 37.6, 53.8; [underlined: Obese at baseline]: 1.2, 0.9, 89.7; [underlined: Change in probability per 1 SD change in predictor, % Normal weight at baseline:] −5.3, 4.3, 0.9; [underlined: Overweight at baseline]: −2.1, −5.3, 7.3; [underlined: Obese at baseline:] −0.3, −2.2, 2.5; [underlined: Unhealthful food score,] p=0.176:; [underlined: Probability at mean change]; [underlined: of predictor, %]; [underlined: Normal weight at baseline:] 79.8, 17.3, 2.7; [underlined: Overweight at baseline:] 8.5, 37.1, 54.3; [underlined: Obese at baseline]: 1.3, 9.5, 89.1; [underlined: Change in probability per 1 SD change in predictor, %]; [underlined: Normal weight at baseline:] −3.5, 3.0, 0.6; [underlined: Overweight at baseline:] −1.5, −3.6, 5.1; [underlined: Obese at baseline]: 1.5, 10.7, 87.6 | [underlined: Key confounders accounted for:] SEP and/or parental or caregiver education; race and/or ethnicity; child's anthropometry at baseline; child sex; parental or caregiver BMI; [underlined: Key confounders NOT accounted for:] none; [underlined: Model adjustments:] Child age, gender, parent BMI, baseline predictors, age difference, study condition, school, socio-economic status (specific to the Bright Start population); [underlined: Funding]: NIH
Gable, 2007^6^; PCS, Early Childhood Longitudinal Study–Kindergarten (ECLS-K), US; Analytic N=8000; Power Analysis: NR; [underlined: Caregiver Characteristics]; - Female: NR; - Age: NR; - SEP and/or Education: Maternal education: ≥ 12th grade: 10%, HS: 30%, vocational/some college: 33%, Bachelor's degree: 18%, Graduate/professional/ doctorate degree: 9%; Medium annual income: $48,000; Households living in poverty: 14%; SES Quintile 1 (lowest): 13%, Quintile 2: 18%, Quintile 3: 21%, Quintile 4: 23%, Quintile 5 (highest): 25%; - Race and/or Ethnicity: Child race/ethnicity: White/non-Hispanic: 63%, African American: 10%, Hispanic: 16%, Asian: 5%, Native Hawaiian/pacific Islander: 2%, American Indian/Alaskan Native: 1%, Multiracial (non-Hispanic): 3%; - BMI: NR; - Other: 2-parent household: 81%; [underlined: Child Characteristics]; - Female: 52%; - Baseline anthropometry: NR; - Milk feeding practices: NR; [underlined: Primary aim:] To identify eating and activity factors associated with school-aged children’s onset of overweight and persistent overweight. | [underlined: Exposures and Comparators:] Frequency of family meals (Continuous); [underlined: CFP Definition:] Sum of number of breakfast and dinner in a typical week; average of T2 & T3 used to predict overweight onset, and average of T2, T3 & T4 was used to predict persistent overweight; [underlined: CFP Assessment Method:] Questionnaire, 2 items; [underlined: Child age at initial exposure measurement:] 68.4 (4.1) mo; [underlined: Outcome(s):] Weight status; [underlined: Outcome assessment method:] Children’s weight and height were measured. Children were categorized based on their body mass index using CDC 2000 Growth Charts as not overweight (<95th percentile) or overweight (>95th percentile). Three groups were identified: never overweight, overweight onset (not OW during KG and 1st grade and OW @ 3rd grade), persistent overweight ( OW during KG and remained OW @ 1st and 3rd grade and of children who became OW @ 1st grade and remained OW at 3rd grade); [underlined: Age(s) at outcome assessment:] 5, 6, 7 y | [underlined: Overweight onset, g±SE, OR (95% CI)]; [underlined: Family meals per week]: −0.07±0.02, 0.93 (0.90–0.97), p<0.001; [underlined: Persistent overweight, g±SE, OR (95% CI)]; [underlined: Family meals per week]: −0.08±0.01, 0.92 (0.90–0.94), p<0.001 | | [underlined: Key confounders accounted for:] SEP and/or parental or caregiver education; race and/or ethnicity; child sex; [underlined: Key confounders NOT]; [underlined: accounted for]: Child's anthropometry at baseline; parental or caregiver BMI; [underlined: Model adjustments:] Child TV hours/wk, child aerobic exercise/d, child opportunities for activity, neighborhood safety, child sex, child race, ethnicity, SES, school level.; [underlined: Funding:] USDA, Economic Research Service, Food Assistance and Nutrition Research Programs
Gregory, 2010^7^; PCS, The Child and Family Health Study, Australia; Analytic N=106; Power Analysis: NR; [underlined: Caregiver Characteristics]; - Mothers: 100%; - Age: 35 (5.2) y; - SEP and/or Education: Tertiary education: 60%; - Race and/or Ethnicity: NR; - BMI: Overweight: 51%; - Other: Married/de facto relationship: 87%,; [underlined: Child Characteristics]; - Female: 51%; - Baseline anthropometry: Overweight/obese: 15%; Pressure to eat: p<0.05; - Milk feeding practices: NR; [underlined: Primary aim:] To examine the extent to which maternal feeding practices prospectively predict the development of eating behavior and BMI in preschool-aged children. | [underlined: Exposures and Comparators:] Pressure to eat, Restriction, Monitoring, Modeling (Continuous); [underlined: CFP Definition:] Per CFQ, Modeling of eating healthy foods; [underlined: CFP Assessment Method:] Child Feeding Questionnaire (CFQ), 3-items (modeling); [underlined: Child age at initial exposure measurement:] 2–4 [Mean (SD): 3.3 (0.8)] y; [underlined: Outcome(s):] Growth; [underlined: Outcome assessment method:] Mothers reported on their child's age, gender, weight and height. Child BMIZ scores were calculated per CDC 2000 growth charts; [underlined: Age(s) at outcome assessment]: 4.3 y | | [underlined: BMIz @~4 y, β]; Monitoring: p≥0.05; [underlined: Modeling:] p≥0.05; Pressure to eat: p≥0.05; Restriction: p≥0.05 | [underlined: Key confounders accounted for:] SEP and/or parental or caregiver education; child sex; parental or caregiver BMI, child's anthropometry at baseline; [underlined: Key confounders NOT accounted for:] Race and/or ethnicity;; [underlined: Model adjustments:] Baseline BMIZ, Child age and gender, maternal age, Maternal BMI, education; [underlined: Funding:] National Heart Foundation Australia
Guerrero, 2016^9^; PCS, Early Childhood Longitudinal Study Birth cohort, U.S.; Analytic N=2441; Power Analysis: NR; [underlined: Caregiver Characteristics]; - Fathers: 100%; - Age: 35 (6.4) y; - SEP and/or Education: < High School: 13.6%, High School: 23.8% College: 24.9%, ≥ Bachelor’s 37.7%; - Father's Employment: 35 or more hours: 92.5%, Less than 35 hours: 3.5%, Unemployed: 4%; Under Federal Poverty Line: 11.1% Race and/or Ethnicity: White: 70.5%, Black: 5.2%, Hispanic: 19.7%, Asian: 3%, Other: 1.6%; - BMI: NR; - Other: Child's primary language in household, English: 83.9%, Spanish: 12.5%, Other: 3.6%; [underlined: Child Characteristics]; - Female: 48%; - Baseline anthropometry: Overweight: 31.5%, Obese: 16.1%; - Milk feeding practices: Child ever breastfed: 78.7%; [underlined: Primary aim:] To examine the associations of father-child feeding and physical interactions with dietary practices and weight status in children. | [underlined: Exposures and Comparators:] Breakfast and dinner with child (Continuous); [underlined: CFP Definition:] Frequency of father having breakfast or dinner with child in a typical week: single item; [underlined: CFP Assessment Method:] Questionnaire Child age at initial exposure measurement: 24 mo; [underlined: Outcome(s):] Weight status; [underlined: Outcome assessment method:] Children’s height and weight were measured by trained field workers during home visits. BMI z-score was calculated and using the CDC growth reference data. Overweight was defined as a BMI between the 85th to 95th percentile and obesity as a BMI at or above the 95% for age and sex.; [underlined: Age(s) at outcome assessment]: 52 (3.9) mo | Overweight @ 48 mo, OR (95% CI); [underlined: Breakfast with father:] 1.09 (1.03, 1.16) | Overweight @ 48 mo, OR (95% CI); [underlined: Dinner with father:] NS (data not reported) | [underlined: Key confounders accounted for:] SEP and/or parental or caregiver education; race and/or ethnicity; child sex; parental BMI; [underlined: Key confounders NOT accounted for:] Child's anthropometry at baseline; [underlined: Model adjustments:] Child sex, child’s age, child’s birth weight status, child care arrangement, child ever breastfed, child age at introduction of solid foods, mother’s weight status, mother’s depression score, mother’s education, mother’s age, number of adults in household over 18, primary language in household, and poverty indicator, father's employment, education, race.; [underlined: Funding:] US Department of Health and Human Services (HRSA) Maternal and Child Health Research Program; Eunice Kennedy Shriver National Institute of Child Health and Human Development (NICHD)

a Abbreviations: BMI: Body Mass Index; BMIz: Body Mass Index Z-score; CFP: Caregiver feeding practice; CFQ: Child Feeding Questionnaire; NR: Not Reported; NA: Not Applicable; SEP: Socioeconomic position

b Food parenting practices that fall within this bucket are underlined.

Table 13 Risk of bias for observational studies examining structured feeding practices (other structured feeding practices) and growth, body composition and risk of obesity^a^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Afonso, 2016^1^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Arcan, 2013^2^ | LOW | SOME CONCERNS | LOW | SOME CONCERNS | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Gable, 2007^6^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Gregory, 2010^7^ | SOME CONCERNS | HIGH | LOW | LOW | HIGH | SOME CONCERNS | SOME CONCERNS | HIGH
Guerrero, 2016^9^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Quah, 2019^16^ | LOW | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Rodgers, 2013^17^ | VERY HIGH | SOME CONCERNS | LOW | LOW | HIGH | SOME CONCERNS | SOME CONCERNS | VERY HIGH

a Possible ratings of low, some concerns, high, very high, no information, or not applicable were determined using the "Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)" tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602. ) *Low risk of bias except for concerns about uncontrolled confounding.

Table 14 Evidence examining the relationship between controlling feeding practices and growth, body composition and risk of obesity^a^,^b^

Study and Population Characteristics | Intervention/Exposure and Comparator, Outcome | Significant Results | Non-Significant Results | Confounders, Model Adjustments, Funding
Hughes, 2021^11^; PCS, U.S.; Analytic N=119; Power Analysis: Power analysis [n=187 with 95% power to detect an effect size of 0.15 for 5 predictor variables]; [underlined: Caregiver Characteristics]; - Mothers: 100%; - Age: 31.45 (6.60) y; - SEP and/or Education: Head start: 100%; Less than high school diploma: 38.3%, High school diploma or equivalent: 24.2%, Some college or more: 37.5%; Currently employed: 21.1%; - Race and/or Ethnicity: Hispanic: 100%; White: 71.9%, American Indian or Alaskan Native: 12.5%, Other (usually indicating Hispanic, Latina, or Mexican): 12.5%, Black or African American: 0.8%; - BMI: NR; - Other: Married: 59.4%, Widowed, separated, divorced: 26.5%, Never married: 14.1%; Parent immigrant status: Born in Mexico: 63.3%, Born in the U.S.: 18.0%, Born in Central America: 17.9%, Born in Cuba: 0.8%; Child born in the U.S.: 96.9%; [underlined: Child Characteristics]; - Female: 53%; - Baseline anthropometry: BMI categories at 4–5 y: Healthy (<85th percentile): 50.0%, Overweight (85th-<95th percentile): 22.7%, Obese (≥95th percentile): 27.3%; - Milk feeding practices: NR; [underlined: Primary aim]: To examine whether or not parental feeding styles at ages 4–5 continued to predict children's weight status at this later time point (7–9 y). To examine the direction of effects between parental feeding styles and child weight status. | [underlined: Exposures and Comparators:] Restriction, Pressure to eat, Monitoring (Continuous); [underlined: CFP Definition:] Per CFQ; [underlined: CFP Assessment Method:] Child Feeding Questionnaire (CFQ); [underlined: Child age at initial exposure measurement:] 4–5 [Mean (SD): 4.73 (0.46)] y; [underlined: Outcome(s):] Growth; [underlined: Outcome assessment method:] Weight and height measured by trained staff. Age- and sex-specific BMI standardized scores calculated based on CDC reference standards.; [underlined: Age(s) at outcome assessment:] 7–9 y [Mean (SD): 8.31 (0.72)] | [underlined: BMIz @ 7–9 y, β]; Monitoring @ 4–5 y: −0.149, p<0.01 | [underlined: BMIz @ 7–9 y, β]; [underlined: Pressure to eat] @ 4–5 y: 0.076; [underlined: Restriction] @ 4–5 y: 0.071 | Key confounders accounted for: SEP and/or parental or caregiver education; race and/or ethnicity; child's anthropometry at baseline; child sex; Key confounders NOT accounted for: Parental or caregiver BMI; Model adjustments: Baseline BMI z-score, child gender, child age, parental acculturation, child eating behaviors (food responsiveness, emotional overeating, satiety responsiveness), parental feeding practices (parental feeding styles only), parental feeding styles (parental feeding practices only); Funding: NICHD; USDA Children's Nutrition Research Center
Power, 2021^15^; PCS, None, U.S.; Analytic N=129; Power Analysis: NR; [underlined: Caregiver Characteristics]; - Mothers: ~98%, Grandmothers: ~2%; - Age: 31.5 (6.6) y; - SEP and/or Education: Education of parent: 8th grade or less: 28.7%, Some high school: 9.3%, High school diploma or GED: 24.0%, Some college or technical school: 31.0%, 4-year college graduate: 7.0%; Currently employed: 21.7%; - Race and/or Ethnicity: Latina: 100%; - BMI: Maternal BMI: Healthy (<25): 16.4%, Overweight (≥25 and <30): 30.5%, Obese (≥30): 53.1%; - Other: Marital status: Married: 59.7%, Never married: 27.2%, Widowed, separated, divorced: 13.2%; Parent immigration status: Born in U.S.: 17.7%, Born in Mexico: 63.3%, Born in Central America: 17.9%, Born in another country: 0.8%; Spanish speaking: 79.1%, English speaking: 20.9%;; [underlined: Child Characteristics]; - Female: 47%; - Baseline anthropometry: Healthy (<85th percentile): 50.4%, Overweight (85th to <95th percentile): 22.5%, Obese (≥95th percentile): 27.1%. NR differences between groups; - Milk feeding practices: NR; [underlined: Primary aim]: To examine longitudinally, over a 3.5-year period, the relationships between feeding practices, feeding styles, and young children's BMI z-scores, using both self-report and observational measures of maternal feeding. | [underlined: Exposures and Comparators:] Restriction, Pressure to eat, Monitoring (Continuous); [underlined: CFP Definition:] Per CFQ; [underlined: CFP Assessment Method]: Child Feeding Questionnaire (CFQ); [underlined: Child age at initial exposure measurement:] 4–5 [Mean (SD): 56.8 (5.5)] mo; [underlined: Outcome(s):] Growth; [underlined: Outcome assessment method:] Height and weight measured by trained staff. Age- and sex-specific BMIZ were calculated based on revised 2000 growth charts from CDC; [underlined: Age(s) at outcome assessment:] 7–9 y | [underlined: BMIz @ 7–9 y, β (SE)]; Monitoring: −0.15 (0.07), p<0.05 | [underlined: BMIz @ 7–9 y, β (SE)]; [underlined: Restriction:] −0.01 (0.08), p≥0.05; [underlined: Pressure to eat:] 0.01 (0.07), p≥0.05 | [underlined: Key confounders accounted for:] Race and/or ethnicity; child's anthropometry at baseline; [underlined: Key confounders NOT accounted for:] SEP and/or parental or caregiver education; child sex; parental or caregiver BMI; [underlined: Model adjustments:] Child's baseline BMI; [underlined: Funding:] NICHD; USDA/ARS
Hughes, 2016^10^; PCS, US; Analytic N=129; Power Analysis: NR; [underlined: Caregiver Characteristics]; - Mothers: 100%; - Age: 32.01 (6.68) y; - SEP and/or Education: High school diploma or less: 62.8%, Some college or more: 37.2%, Currently employed: 24.0%; Married: 55.8%, never married: 13.2%, widowed, separated, divorced: 31%; - Race and/or Ethnicity: Latina: 100%; - BMI: NR; - Other: Parent immigrant status: born in US:; - 15.5%, born in Mexico: 64.3%, born in Central America: 20.2%; [underlined: Child Characteristics]; - Female: 45%; - Baseline anthropometry: Normal weight: 48.8%, Overweight: 21.7%, Obese: 29.5%, NR differences bw groups; - Milk feeding practices: NR; [underlined: Primary aim:] To investigate the influence of feeding styles and food parenting practices on low-income children's weight status over time. | [underlined: Exposures and Comparators:] Restriction, Pressure to eat, Monitoring (Continuous); [underlined: CFP Definition:]; - Restriction: limiting child access to certain foods,; - Pressure to eat: making sure the child is eating all food on her plate,; - Monitoring: keeping track of the child’s intake of snacks and high fat foods; [underlined: CFP Assessment Method:] Child Feeding Questionnaire (CFQ); [underlined: Child age at initial exposure measurement:] 4–5 y; [underlined: Outcome(s):] Growth; [underlined: Outcome assessment method:] Weight and height were measured by trained staff members. CDC reference standards were used to generate age- and gender-specific BMI z-scores.; [underlined: Age(s) at outcome assessment]: 6 y | [underlined: BMIz @ 6 y, β]; [underlined: Restriction]: 0.082, p<0.05; Monitoring: −0.068, p<0.05 | [underlined: BMIz @ 6 y, β]; [underlined: Pressure to eat]: 0.038, p>0.05 | [underlined: Key confounders accounted for:] race and/or ethnicity; child's anthropometry at baseline; child sex; [underlined: Key confounders NOT accounted for:] SEP and/or parental or caregiver education; parental BMI; [underlined: Model adjustments:] Child sex, child age in months, child BMIz at baseline, acculturation (English domain), parent born in US, food responsiveness, emotional overeating, satiety responsiveness; [underlined: Funding:] NICHD, USDA-ARS
Farrow, 2018^25^; PCS, UK; Analytic N=39; Power Analysis: NR; [underlined: Caregiver Characteristics]; - Mothers: 100%; - Age: NR; - SEP and/or Education: Years of post-16 education: 4 (3.01) y; - Race and/or Ethnicity: White British: 83%; - BMI: Maternal BMI: 24.76 (5.01); - Other: NA; [underlined: Child Characteristics]; - Female: 47%; - Baseline anthropometry: BMI z-score: 0.09 (1.00); - Milk feeding practices: NR; [underlined: Primary aim:] 1. To explore the efficacy of using a novel approach to observe maternal verbal and physical feeding restriction by providing a commonly restricted food during a laboratory mealtime. 2. To evaluate whether observed maternal restriction of food, and children’s responses to this (i.e., acceptance or rejection of restriction), predict child BMI z-scores 2 years later | [underlined: Exposures and Comparators:] Restriction (verbal; physical) by mother (Continuous); [underlined: CFP Definition:]; Frequency was recorded for:; - Verbal restriction of food: e.g., "Don’t eat that cookie now";; - Physical restriction of food: e.g., removal of a food from the child's plate.; [underlined: CFP Assessment Method]: Family mealtime coding system (FMCS); Child age at initial exposure measurement: 3–5 y; [underlined: Child age at initial exposure measurement:] 3–5 y; [underlined: Outcome(s):] Growth; [underlined: Outcome assessment method:] Weight and height measured by research staff. Weight and height scores converted to age- and gender-adjusted BMI z-scores using Child Growth Foundation Reference Curves.; [underlined: Age(s) at outcome assessment]: 5–7 y | [underlined: BMIz @ 5–7 y, Partial correlations]; [underlined: Restriction (verbal):] 0.34, p≤0.05; [underlined: Restriction (physical):] 0.47, p<0.01 | | [underlined: Key confounders accounted for:] Child's anthropometry at baseline; child sex; parental or caregiver BMI; [underlined: Key confounders NOT accounted for:] SEP and/or parental or caregiver education; race and/or ethnicity; [underlined: Model adjustments]: Maternal BMI, child BMIz at baseline; [underlined: Funding:] University institutions of authors.
Derks, 2017^24^; PCS, Generation R, Netherlands; Analytic N=4689; Power Analysis: NR; [underlined: Caregiver Characteristics]; - Mothers: 100%; - Age: NR; - SEP and/or Education: Household income: Low, <1600 €/mo: 12.4%, Medium, 1600-4000€/mo:49.8%, High, >4000 €/mo: 37.8% Race and/or Ethnicity: Child ethnicity: Dutch: 65.1%, Non-Western: 26.0%, Other Western: 8.9%; - BMI: 25.34 (4.74); - Other: NA; [underlined: Child Characteristics]; - Female: 51%; - Baseline anthropometry: BMI @ 4 y: 15.80 (1.31), NR differences bw groups; - Milk feeding practices: NR; [underlined: Primary aim:] To examine the direction of effects between restrictive feeding and child adiposity and to explore a possible mediating role of maternal concern about child weight. | [underlined: Exposures and Comparators:] Restrictive feeding (Continuous); [underlined: CFP Definition:] Per CFPQ; [underlined: CFP Assessment Method:] Child Feeding Practices Questionnaire (CFPQ); [underlined: Child age at initial exposure measurement:] 4 y; [underlined: Outcome(s):] Growth; [underlined: Outcome assessment method:] Height and weight measured by trained health professionals/ researchers. Age- and sex-adjusted BMI SD (z) scores based on Dutch reference growth curves.; [underlined: Age(s) at outcome assessment:] 10 y | | [underlined: BMIz @ 10 y, β (95% CI)]; [underlined: Restrictive feeding]: 0.00 (−0.04, 0.05), p=0.88 | [underlined: Key confounders accounted for:] SEP and/or parental or caregiver education; race and/or ethnicity; child's anthropometry at baseline; parental or caregiver BMI; [underlined: Key confounders NOT accounted for:] child sex; [underlined: Model adjustments:] child ethnicity, birth weight, maternal depressive symptoms, maternal BMI, and household income, BMIz SD score at baseline (4 y); [underlined: Funding:] Dutch Diabetes Foundation grant
Gubbels, 2011^8^; PCS, KOALA Birth Cohort Study, Netherlands; Analytic N=1513; Power Analysis: NR; [underlined: Caregiver Characteristics]; - Female: NR; - Age: Maternal age at birth: 32.2 (3.7); - SEP and/or Education: Educational level Mothers: High: 54.1%, Medium: 38.0%, Low: 7.9%; Fathers: High: 53.2%, Medium: 33.9%, Low: 12.9%; Average h worked per wk: Mothers: 18.0 (11.1) h/wk, Fathers: 37.8 (10.1) h/wk; - Race and/or Ethnicity: Country of birth: Mother: Netherlands: 97.0%, Other: 3%; Fathers: Netherlands: 96.3%, Other: 3.7%; - BMI: Maternal BMI: 24.0 (3.8), Paternal BMI: 25.0 (3.1); - Other: NA; [underlined: Child Characteristics]; - Female: 49%; - Baseline anthropometry: BMIz @ 5 y: −0.27 (0.99); Restriction: p<0.001, Stimulation healthy intake: p<0.07; - Milk feeding practices: NR; [underlined: Primary aim:] To examine parental and child associates of energy-balanced related parenting practices; to examine the association between energy balance-related parenting and activity behavior and dietary intake in 5-year-old children, and well as the prospective influence on children's BMI development up to age 7; to examine whether child background characteristics moderated the impact of the parenting practice. | [underlined: Exposures and Comparators]: Restriction of unhealthy intake, Monitoring, Stimulation healthy intake (Continuous); [underlined: CFP Definition]:; - Restriction and monitoring - Per CFQ; - Stimulation healthy intake assessed using items "I make sure that my child eats enough healthy food products" and "I get my child enthusiastic about healthy products, such as vegetables, fruit, and whole meal products"; [underlined: CFP Assessment Method:] Child Feeding Questionnaire (CFQ)-modified; [underlined: Child age at initial exposure measurement:] 5 y; [underlined: Outcome(s):] Growth; [underlined: Outcome assessment method:] Child's height and weight were reported by parents and used to calculated BMI. BMIz were calculated using the 1997 national reference population (i.e., the Fourth Dutch National Growth Study). Underweight @ 5 y defined as BMIz <5th percentile; [underlined: Age(s) at outcome assessment:] 7 y | [underlined: Full sample (N= 1513)]; [underlined: BMIz @ 7 y, β]; Stimulation healthy intake: −0.06, p<0.05; Sample excluding underweight children @ 5 (N= 1326); [underlined: BMIz @ 7 y, β]; Stimulation healthy intake: −0.07, p<0.05 | [underlined: Full sample (N=1513) BMIz @ 7 y, β]; [underlined: Restriction]: 0.01, p>0.05; Monitoring: 0.02, p>0.05; Sample excluding underweight children @ 5 (N= 1326); [underlined: BMIz @ 7 y, β]; [underlined: Restriction:] 0.01, p>0.05; Monitoring: 0.03, p>0.05 | [underlined: Key confounders accounted for:] SEP and/or parental or caregiver education; race and/or ethnicity; child's anthropometry at baseline; child sex; parental or caregiver BMI; [underlined: Key confounders NOT accounted for:] none; [underlined: Model adjustments:] Child gender, birth weight, BMIz @ 5 y, activity style, hungry eating style, picky eating style, parental BMI, employment, educational level, country of birth, and maternal age.; [underlined: Funding:] Dutch Ministry of Economic Affairs. Dutch Ministry of Health, Welfare and Sports, FrieslandCampina, and the Dutch Sugar Bureau
Afonso, 2016^1^; PCS, Generation XXI, Portugal; Analytic N=4643; Power Analysis: NR; [underlined: Caregiver Characteristics]; - Mothers: 100%; - Age: 34.4 (5.11) y; - SEP and/or Education: Years of schooling: 11.5 (4.21) y; - Race and/or Ethnicity: NR; - BMI: 26.3 (5.04); - Other: NA; [underlined: Child Characteristics]; - Female: 49%; - Baseline anthropometry: BMI @ 4 y: 16.2 (1.73), BMIz @ 4 y: 0.6 (1.08), NR differences bw groups; - Milk feeding practices: NR; [underlined: Primary aim:] To examine bidirectional associations between parental child-feeding practices and BMI at 4 and 7 y | [underlined: Exposures and Comparators:] Restriction, pressure to eat, monitoring, overt control, covert control (Continuous); [underlined: CFP Definition:]; - Restriction, pressure to eat, monitoring - Per CFQ; - Overt control: represented by a firm attitude from parents about what, how much, where, and when the child eats, which can be perceived by the child; - Covert control: child is unable to detect the control; for example, avoiding buying energy-dense foods; [underlined: CFP Assessment Method:] Child Feeding Questionnaire (CFQ); Overt and Covert Control Scale; [underlined: Child age at initial exposure measurement:] 4 y; [underlined: Outcome(s):] Growth; [underlined: Outcome assessment method:] Child weight and height were measured by trained staff and used to calculate BMI. BMI was converted age- and sex-specific BMI SD score (BMIz) according to WHO Growth References.; [underlined: Age(s) at outcome assessment]: 7 y | [underlined: BMIz @ 7 y, β (95% CI)]; [underlined: Pressure to eat:] −0.05 (−0.08, −0.03), p<0.05; [underlined: Overt control:] −0.05 (−0.09, −0.01), p<0.05 | [underlined: BMIz @ 7 y, β (95% CI)]; [underlined: Restriction:] 0.02 (−0.01, 0.05), p>0.05; Monitoring: −0.01(−0.04, 0.02), p>0.05; Covert control: −0.02 (−0.04, 0.01), p>0.05 | [underlined: Key confounders accounted for:] SEP and/or parental or caregiver education; child's anthropometry at baseline; child sex; parental or caregiver BMI; [underlined: Key confounders NOT accounted for:] race/ethnicity; [underlined: Model adjustments]: child's sex, mother's age, educational level, maternal BMI, child BMIz at baseline; [underlined: Funding:] Health XXI Operational Programme, III Community Support Framework and North Regional Health Administration, European Regional Development Fund, Operational Competitiveness Program, Portuguese Foundation for Science and Technology Portuguese Ministry of Education and Science, Calouste Gulbenkian Foundation
Bergmeier, 2016^19^; PCS, Australia; Analytic N=72; Power Analysis: NR; [underlined: Caregiver Characteristics]; - Mothers: 100%; - Age: 36.71 (4.34 ) y; - SEP and/or Education: Annual family income: >A$105,000:39.6%, <A$25,000:4.7%; Tertiary qualification achieved: 70.7%; - Race and/or Ethnicity: Maternal country of birth: Australia: 81.5%, Europe: 7.7%, New Zealand: 3.1%, North America: 3.1%, South Africa: 3.1%, Asia: 1.5%; - BMI: Obese: 16.2%, Overweight: 41.9%,; - Healthy weight: 41.9%; - Other: NA; [underlined: Child Characteristics]; - Female: 56%; - Baseline anthropometry: Obese: 0%, Overweight: 21.2%, Normal weight: 75.8%, Underweight: 3.0%; NR differences bw groups; - Milk feeding practices: NR; [underlined: Primary aim:] To validate the Mutually Responsive Orientation (MRO) coding system adapted for assessing parent-child interaction during food preparation and consumption situations. | [underlined: Exposures and Comparators:] Responsiveness, control (mild control, assertive control, forceful control) (Continuous); [underlined: CFP Definition]:; - Responsiveness in meal preparation and consumption contexts (average responsiveness scores across 3-minute segments); - Control: control issues related to food issues in food preparation and food consumption contexts (overall composite score and relative frequency scores for mild, assertive and forceful control in relation to outcome measures).; [underlined: CFP Assessment Method:] Coding system developed by authors; [underlined: Child age at initial exposure measurement]: 3 y; [underlined: Outcome(s):] Growth; [underlined: Outcome assessment method:] Child weight and height were measured by trained research assistants at home visits and used to calculate BMIz according to CDC reference curves. Weight status (normal weight, overweight, or obese) was determined using sex- and age-adjusted BMIz values according to criteria from CDC; [underlined: Age(s) at outcome assessment]: 4 y | [underlined: Child BMIz @ 4 y, β]; Model 3:; Responsiveness: 0.23, p≤0.05; Model 4:; Responsiveness: 0.22, p≤0.05 | [underlined: Child BMIz @ 4 y, β]; Model 1:; [underlined: Control:] 0.10, p>0.05; Model 2:; Responsiveness: −0.03, p>0.05; [underlined: Mild Control:] −0.10, P>0.05; Model 3:; [underlined: Assertive control:] 0.12, p>0.05; Model 4:; [underlined: Forceful control:] 0.06, p>0.05 | [underlined: Key confounders accounted for:] SEP and/or parental or caregiver education; child's anthropometry at baseline; parental or caregiver BMI; [underlined: Key confounders NOT accounted for:] race/ethnicity; child sex; [underlined: Model adjustments:] All models: Maternal BMI, family income, approach temperament, Child BMIz at baseline; Model 1: + Mutually responsive orientation, committed compliance; Model 2, 3, 4: + Child responsiveness; [underlined: Funding:] Australian Research Council Discovery Grant
Jansen, 2020^28^; PCS, Generation R, Netherlands; Analytic N=3642; Power Analysis: NA; [underlined: Caregiver Characteristics]; - Mothers: 86.4%; - Age: NR; - SEP and/or Education: Maternal education level: low: 10.7%, Mid-low: 27.3%, Mid−high: 26.7%, High: 35.3%; Paternal education level: Low: 14.6%, Mid-low: 26.9%, Mid-High: 22.3%, High: 36.2%; - Race and/or Ethnicity: Child ethnicity: Dutch: 70.6%, Other Western: 9.1%, Non−Western: 20.3%; - BMI: Maternal BMI: 24.2 (3.9); Paternal BMI: 25.1 (3.2); - Other: NA; [underlined: Child Characteristics]; - Female: 51%; - Baseline anthropometry: BMI @ 4 y: 15.8 (1.3), p=0.58, NR differences bw groups; - Milk feeding practices: NR; [underlined: Primary aim]: To examine the temporal association of using food as reward with eating behavior, body mass index, and weight status of children. | [underlined: Exposures and Comparators:] Using food as reward (Continuous); [underlined: CFP Definition:] The use of food as a reward to motivate, promote, and reinforce good behavior and proper performances, also called "instrumental feeding"; [underlined: CFP Assessment Method:] Child Feeding Questionnaire (CFQ); [underlined: Child age at initial exposure measurement:] 4 y; [underlined: Outcome(s):] Growth, Weight status; [underlined: Outcome assessment method:] Height and weight were measured by trained staff at age 4 and 9 y and used to calculate BMI. Sex- and age-adjusted BMI Z-scores were calculated using Dutch growth references.; IOTF cutoffs were used to classify children as underweight/normal weight or as having overweight/obesity.; [underlined: Age(s) at outcome assessment:] 9 y | [underlined: Overweight/obesity @ 9 y,]; [underlined: OR (95% CI)]; [underlined: Using food as reward:] 0.99 (0.95, 1.05) | [underlined: BMIz @ 9 y, β (95% CI)]; [underlined: Using food as reward]: −0.02 (−0.05, 0.01) | [underlined: Key confounders accounted for:] SEP and/or parental or caregiver education; race and/or ethnicity; child's anthropometry at baseline; child sex; parental or caregiver BMI; [underlined: Key confounders NOT accounted for:] none; [underlined: Model adjustments:] Child sex, child ethnicity, mothers' and fathers' education, mothers' and fathers' BMI, child baseline BMI; [underlined: Funding:] The Netherlands Organization for Health Research and Development, the China Scholarship Council, the Dutch Heart Foundation, the Dutch Diabetes Foundation
Berkowitz, 2010^21^; PCS, IGC cohort, US; Analytic N=61; Power Analysis: NR; [underlined: Caregiver Characteristics]; - Mothers: 80%; - Age: NR; - SEP and/or Education: Income < $30,000: HR: 15.2%, LR: 8.1%; - Race and/or Ethnicity: White: 100%; - BMI: Maternal pre-pregnancy BMI: HR: 30.4 (4.2); LR: 19.6 (1.12); Paternal BMI at child's birth: HR: 27.25 (4.06), LR: 24.92 (2.49); - Other: NA; [underlined: Child Characteristics]; - Female: 49%; - Baseline anthropometry: BMI @ 4 y: ~16; Total skinfold thickness @ 4 y: ~ 27 mm; Total body fat @ 4 y: ~3.5 kg; Total % body fat @ 4 y: ~20.5; Waist circumference @ 4 y: ~53.5 cm; NS bw groups; - Milk feeding practices: NR; [underlined: Primary aim:] To test whether child rate of eating and parental prompts during a laboratory meal at age 4 y differ among children born at HR and LR for obesity in the IGS cohort, and to test whether these same children eating, and parental feeding measures were associated with an increased risk of child overweight status at age 6 y. | [underlined: Exposures and Comparators:] Restriction (Continuous); [underlined: CFP Definition:] Definitions adapted from mealtime observation scale:; - Parental prompts (for the child to eat),; - Parental Discouragements (of eating); [underlined: CFP Assessment Method:] Child Feeding Questionnaire (CFQ); [underlined: Child age at initial exposure measurement:] 4 y; [underlined: Outcome(s):] Growth, Body composition, Weight status; [underlined: Outcome assessment method:] Anthropometric and body composition measurements were measured at the Laboratory. Height and weight were used to calculate BMI. BMI was converted into percentiles using the CDC growth charts.; Overweight/ obese was defines as BMI% ≥ 85th percentile. Biceps, triceps, subscapular, and suprailiac skinfold thickness were added together to calculate a sum. Dual-energy X-ray absorptiometry was used to measure total and percentage fat mass and lean mass; [underlined: Age(s) at outcome assessment:] 6 y | | [underlined: Change in BMI 4–6 y, results not presented]; [underlined: Parental prompts:] p>0.05; [underlined: Parental discouragements:] p>0.05; [underlined: Change in Total skinfold thickness, Change in Total body fat, Change in % body fat 4–6 y, results not presented]; [underlined: Parental prompts:] p>0.05; [underlined: Parental discouragements:] p>0.05; [underlined: Overweight (n=11) vs. Normal weight (n=50 ) @ 6 y, Mean (SD)]; [underlined: Parental prompts/min:] 3.47 (1.42) vs. 2.95 (1.35), p=0.28; [underlined: Parental discouragements/min:] 0.20 (0.13) vs. 0.18 (0.22), p=0.83 | [underlined: Key confounders accounted for:] Child sex; parental or caregiver BMI; [underlined: Key confounders NOT accounted for:] SEP and/or parental or caregiver education; race and/or ethnicity; child's anthropometry at baseline; [underlined: Model adjustments:] Pre-pregnancy BMI, child gender and paternal BMI (changes in child BMI, waist circumference, total body fat measures, and lean body mass only); [underlined: Funding:] NIH, Translational Research Center, and the Nutrition Center of the Children's Hospital of Philadelphia
Fulkerson, 2013^26^; PCS, Bright Start, US; Analytic N=422; Power Analysis: NR; [underlined: Caregiver Characteristics]; - Mother: 67.9%, Grandmother: 15.4%, Father: 8.7%, Other: 8.0%; - Age: 35.7 (10.8) y; - SEP and/or Education: NR; - Race and/or Ethnicity: Child race/ethnicity: American Indian: 100%; - BMI: BMI @ baseline: 32.4 (7.3); - Other: Marital status: Single/never married: 30%, Married: 29%, Not married, living with partner: 21%, Separated: 7%, Divorced: 10%, Widowed: 3%; [underlined: Child Characteristics]; - Female: 49%; - Baseline anthropometry: BMIz: 0.49 (1.18), NS differences bw groups; - Milk feeding practices: NR; [underlined: Primary aim]: To assess cross-sectional and prospective associations between scores on Food Responsiveness and Parental Control scales with 6 anthropometric outcomes (child weight status, BMIz, triceps and subscapular skinfolds, waist circumference, and % body fat) among high-risk American Indian children. | [underlined: Exposures and Comparators:] Control (Continuous); [underlined: CFP Definition:] Per PFSQ; Parental Control Scale; [underlined: CFP Assessment Method:] Parental Feeding Style Questionnaire (PFSQ); [underlined: Child age at initial exposure measurement:] 5.8 (0.5) y; [underlined: Outcome(s):] Growth, Body composition, Weight status; [underlined: Outcome assessment method:] Child's anthropometry (height, weight, waist circumference, triceps and subscapular skinfolds) was measured by trained staff. Height and weight were used to calculate age- and sex-adjusted BMI percentile scores using CDC growth reference.; Underweight was defined as BMI≤5th percentile, normal weight defined as BMI >5th and ≤84th percentile, overweight/obese was defines as BMI≥85th percentile. % body fat was assessed using Tanita scales. Parent overweight/obese status was calculated as BMI>25, normal weight status was BMI between 18.5 and 25, and underweight was BMI <18.5.; [underlined: Age(s) at outcome assessment:] 7 y | | [underlined: BMIz @ 7 y, β (SE)]; Boys:; [underlined: Control:] 0.09 (0.12), p>0.05; Girls:; [underlined: Control:] −0.15 (0.08), p>0.05; [underlined: Subscapular skinfold @ 7 y,]; [underlined: β (SE)]; Boys:; [underlined: Control:] 0.49 (0.47), p>0.05; Girls:; [underlined: Control:] −0.69 (0.47), p>0.05; [underlined: Triceps skinfold @ 7 y, β]; [underlined: (SE)]; Boys:; [underlined: Control:] −0.17 (0.56), p>0.05; Girls:; [underlined: Control:] −0.67 (0.52), p>0.05; [underlined: Waist circumference @ 7 y,]; [underlined: β (SE)]; Boys:; [underlined: Control:] 0.66 (0.77), p>0.05; Girls:; [underlined: Control:] 0.60 (0.84), p>0.05; [underlined: % Body fat @ 7 y, β (SE)]; Boys:; [underlined: Control:] 0.16 (0.67), p>0.05; Girls:; [underlined: Control:] −0.63 (0.78), p>0.05; [underlined: Overweight status @ 7 y, β]; [underlined: (SE)]; Boys:; [underlined: Control:] −0.03 (0.06), p>0.05; Girls:; [underlined: Control:] −0.08 (0.05), p>0.05 | [underlined: Key confounders accounted for:] Race and/or ethnicity; child's anthropometry at baseline; child sex; [underlined: Key confounders NOT accounted for:] SEP and/or parental or caregiver education, parental or caregiver BMI; [underlined: Model adjustments:] Baseline values (anthropometric outcomes), treatment condition, random effect of school; [underlined: Funding:] NIH
Rhee, 2009^30^; PCS, Study of Early Child Care and Youth Development, US; Analytic N=789; Power Analysis: NR; [underlined: Caregiver Characteristics]; - Mothers: 100%; - Age: NR; - SEP and/or Education: Maternal education: 14.61 (2.39) y; - Race and/or Ethnicity: White: 83.8%, Other: 16.2%; - BMI: Maternal FRS score: 4.58 (1.43); - Other: NA; [underlined: Child Characteristics]; - Female: 52%; - Baseline anthropometry: BMIZ: 0.34 (1.03), NS differences bw groups; - Milk feeding practices: NR; [underlined: Primary aim:] To examine the temporal relationship between controlling maternal feeding practices (CMFPs) and child weight status, specifically, whether changes in CMFP preceded or followed changes in BMIz. | [underlined: Exposures and Comparators:] Controlling feeding practices (Continuous, Categorical: More controlling vs. less controlling vs. no change); [underlined: CFP Definition:] Do you let your child eat what he/she feels like eating?; [underlined: CFP Assessment Method:] Questionnaire (single item); [underlined: Child age at initial exposure measurement]: 4, 7 y; [underlined: Outcome(s):] Growth; [underlined: Outcome assessment method:] Child height and weight were measured during laboratory visits and used to calculate BMI. BMIz were derived using National Center for Health Statistics growth curves (standardized for age and gender). Changes in BMIz were calculated between 4 and 7 years and between 7 and 9 years.; [underlined: Age(s) at outcome assessment]: 7–9 y | [underlined: BMIz increase from 7–9 y, OR (95% CI)]; Boys:; [underlined: More controlling vs. No change:] 0.52 (0.27, 1.00), p<0.05; [underlined: More controlling vs. No change]: 1.00 (0.54, 1.83), p≥0.05; [underlined: Less controlling vs. No change:] 1.06 (0.52, 2.17), p≥0.05 | [underlined: BMIz increase from 7–9 y, OR (95% CI)]; Girls:; [underlined: CMFP @ 4 y:] 1.05 (0.67, 1.66), p≥0.05 | [underlined: Key confounders accounted for:] SEP and/or parental or caregiver education; race and/or ethnicity; child's anthropometry at baseline; child sex; [underlined: Key confounders NOT accounted for:] Parental or caregiver BMI; [underlined: Model adjustments:] Race, maternal education in years, maternal FRS score, child weight status at 4 y, baseline CMFP at 4 y (models examining change in BMIz only); [underlined: Funding:] American Heart Association, Hasbro Pediatric Research Fund
Rodgers, 2013^17^; PCS, Australia; Analytic N=323; Power Analysis: NR; [underlined: Caregiver Characteristics]; - Mother: 100%; - Age: 35 (0.37) y; - SEP and/or Education: Maternal education: University course completed: 73.7%, Some additional training: 9.0%, Secondary school completed: 11.8%, Some secondary school: 5.0%; Income: <$20,000: 2.7%, $20,000−$60,000: 22.5%, $61,000-$100,000:37.0%, $101,000–$140,000: 18.0%, >$140,000: 19.8%; - Race and/or Ethnicity: NR; - BMI: Maternal BMI: 24.21 (4.66); - Other: NA; [underlined: Child Characteristics]; - Female: NR; - Baseline anthropometry: BMIz @ 2 y: 0.30; NR differences bw groups; - Milk feeding practices: NR; [underlined: Primary aim:] To explore prospective relationships between maternal feeding practice, child weight gain and obesogenic behaviors in 2-year-old children. | [underlined: Exposures and Comparators:] Instrumental feeding, Encouragement, Emotional feeding, Control, Covert control, Monitoring, Pushing to eat more, Fat restriction, Weight restriction (Continuous); [underlined: CFP Definition]: Maternal feeding practice components derived using principal component analysis with 78 maternal feeding practice items from the Child Feeding Questionnaire (CFQ), Preschooler Feeding Questionnaire (PFQ), Parent Feeding Style Questionnaire (PFSQ), Control over Eating Questionnaire (COEQ), and Comprehensive Feeding Practices Questionnaire (CFPQ).; [underlined: CFP Assessment Method:] Child Feeding Questionnaire (CFQ), Preschooler Feeding Questionnaire (PFQ), Parent Feeding Style Questionnaire (PFSQ), Control over Eating Questionnaire (COEQ), Comprehensive Feeding Practices Questionnaire (CFPQ); [underlined: Child age at initial exposure measurement:] 1.5–2.5 [Mean (SD): 2.03 (0.37)] y; [underlined: Outcome(s):] Growth; [underlined: Outcome assessment method:] At baseline, all children had weight and height measured by researchers. At follow-up, children's weight and height were measured by researchers (64.1%) or obtained from health records or parent report (35.9%).; Height and weight were used to calculate BMI which were converted to age- and gender-adjusted BMIz.; [underlined: Age(s) at outcome assessment:] 3y | [underlined: BMIz change 2–3 y, pearson product-moment correlation Instrumental feeding:] 0.19, p<0.01 | [underlined: BMIz change 2–3 y, pearson product-moment correlation Control:] −0.08, p≥0.05; [underlined: Covert control:] −0.03, p≥0.05; [underlined: Pushing to eat more:] 0.00, p≥0.05; [underlined: Fat restriction:] −0.01, p≥0.05; [underlined: Weight restriction:] −0.08, p≥0.05; Monitoring: 0.02, p≥0.05; Encouragement: 0.01, p≥0.05; Emotional feeding: −0.04, p≥0.05 | [underlined: Key confounders accounted for:] Child anthropometry at baseline; [underlined: Key confounders NOT accounted for:] SEP and/or parental or caregiver education; race and/or ethnicity; ; child sex; parental or caregiver BMI; [underlined: Model adjustments:] none; [underlined: Funding:] National Heart Foundation Australia
Rodgers, 2013^31^; PCS, Australia; Analytic N=218; Power Analysis: NR; [underlined: Caregiver Characteristics]; - Mother: 100%; - Age: 35 (0.46) y; - SEP and/or Education: Completed a University course: 74%; Very low income (<$A20,000): 2.7%, Low income ($A20,001−$A60,000): 22.5%, Medium income ($A61,001-$A100,000): 37%, High income (>$A101,000): 37.8%; - Race and/or Ethnicity: NR; - BMI: Maternal BMI: 23.93 (4.05); - Other: Mothers born in Australia: 76%; [underlined: Child Characteristics]; - Female: 53%; - Baseline anthropometry: BMIz @ 2 y: 0.29 (1.18); Differences bw groups p<0.05; - Milk feeding practices: NR; [underlined: Primary aim:] To test a model in which mothers' BMI, body dissatisfaction, dietary restraint, and concerns about their child's weight were related to restrictive feeding practices and child BMIz change. | [underlined: Exposures and Comparators:] Weight-focused restrictive feeding (Continuous); [underlined: CFP Definition:] Parents' restriction of all types of food explicitly in order to control their child's weight; [underlined: CFP Assessment Method:] Comprehensive Feeding Practices Questionnaire (CFPQ-Restriction for weight-control subscale); [underlined: Child age at initial exposure measurement:] Mean (SD): 2.03 (0.37) y; [underlined: Outcome(s):] Growth; [underlined: Outcome assessment method:] At baseline, all children had weight and height measured by researchers. At follow-up, children's weight and height were measured by researchers (64.1%) or obtained from health records or parent report (35.9%).; Height and weight were used to calculate BMI which were converted to age- and gender-adjusted BMIz based on population growth references from National Center for Health Statistics; [underlined: Age(s) at outcome assessment:] 3 y | | [underlined: BMIz change 2–3 y, Spearman correlation Restriction:] −0.05, p>0.05; [underlined: BMIz change 2–3 y, path analysis]; [underlined: Restriction:] −0.06, p=0.349 | [underlined: Key confounders accounted for:] parental or caregiver BMI; [underlined: Key confounders NOT accounted for:] SEP and/or parental or caregiver education; race and/or ethnicity; child sex, child anthropometry at baseline; [underlined: Model adjustments:] Maternal BMI (path analysis only); [underlined: Funding]: National Heart Foundation Australia
Eichler, 2019^4^; PCS, Leipzig Research Center for Civilization; Diseases (LIFE) Child Study, Germany; Analytic N=1,512 (n=299 to 416 at any time point); Power Analysis: Power analysis [n=299–416 per group with a=0.05 to detect medium (Cohen's d=0.5) or large (Cohen's d=0.8) effect]; [underlined: Caregiver Characteristics]; - Parents: 100%; - Age: NR; - SEP and/or Education: SES: Low: ~7%, Medium: ~47%, High: ~46%; - Race and/or Ethnicity: NR; - BMI: NR; - Other: NR; [underlined: Child Characteristics]; - Female: ~47%; - Baseline anthropometry: BMIz: Underweight: ~1%, Normal weight: ~89%, Overweight: ~5%, Obesity: ~4%; BMIz: ~0.22; - Milk feeding practices: NR; [underlined: Primary aim:] To determine the stability and continuity of parental feeding practices and child zBMI, and their bi-directional associations in a large longitudinal population-based sample of 2- to 12-year-old German children. | [underlined: Exposures and Comparators:] Restrictive feeding, Food as reward, Pressure to eat, Monitoring (Continuous); [underlined: CFP Definition:] Per CFQ; [underlined: CFP Assessment Method:] Child Feeding Questionnaire (CFQ); [underlined: Child age at initial exposure measurement:] 2–3, 3–4, 4–5, 5–6, 6–7, 7–8, 8−9, 9–10, 10–11 y; [underlined: Outcome(s):] Growth; [underlined: Outcome assessment method:] Height and weight measured by research staff. Sex- and age-specific BMI z-scores based on Kromeyer-Hauschild (2002) reference; [underlined: Age(s) at outcome assessment:] 3, 4, 5, 6, 7, 8, 9, 10, 11, 12 y | | [underlined: BMIz @ 3, 4, 5, 6, 7, 8, 9, 10,]; [underlined: 11, 12 y]; [underlined: Food as reward @ 2, 3, 4, 5 y on BMI after 1-y follow-up:] Data NR, NS; [underlined: Pressure to eat @ 2, 3, 4, 5 y on BMI after 1-y follow-up:] Data NR, NS; [underlined: Restriction @ 2, 3, 4, 5 y on BMI after 1-y follow-up:] Data NR, NS | [underlined: Key confounders accounted for:] SEP and/or parental or caregiver education; child sex; [underlined: Key confounders NOT accounted for:] Race and/or ethnicity; child's anthropometry at baseline; parental or caregiver BMI; [underlined: Model adjustments:] Child sex, SES, parenting feeding practices @ baseline and 1 y follow up, BMIz @ baseline and 1 y follow-up; [underlined: Funding:] Leipzig Research Centre for Civilization Diseases; Integrated Research and Treatment Center Adiposity Diseases of Leipzig University; European Union; European Regional Development Fund; Free State of Saxony.
Souto-Gallardo, 2020^18^; PCS, Juega, Mexico; Analytic N=91; Power Analysis: NR; [underlined: Caregiver Characteristics]; - Mothers: 98.1%; - Age: 31.7 (7.1) y; - SEP and/or Education: Less than high school: 35.2%, High school: 18.7%, College: 46.2%; Family income per mo: ≤$265/mo: 37.8%, $265−530/mo: 37.8%, >$530/mo: 24.4%; - Race and/or Ethnicity: Mexican: 100%; - BMI: BMI: 29.1 (6.4); Normal weight: 25.3%, Overweight: 37.4%, Obesity: 37.4%; WC (Mean (25th, 75th percentile): 94.0 (82, 103); WC (% > 90th percentile): 77.5%; - Other: NA; [underlined: Child Characteristics]; - Female: 52%; - Baseline anthropometry: BMIZ at baseline (Mean, 25th, 75th percentile): 1.2 (0.4, 1.5); Baseline weight status: Underweight (≤2.0 SD): 0.0%, Normal weight: (−1.99 SD ≤ 1.0 SD) 50.0%, High risk of overweight (>1.0 SD ≤ 2.0 SD): 36.5%, Overweight (>2.0 SD ≤ 3.0 SD): 5.4%,Obesity (>3.0 SD): 8.1%; WC (% ≥90th percentile): 54.0%, Mean (25th, 75th percentile):; - Milk feeding practices: NR; [underlined: Primary aim:] To evaluate the association between food parenting practices and weight status (BMIz and waist circumference [WC]) among Mexican preschoolers and the directionality of this association after 12 months of follow-up. | [underlined: Exposures and Comparators:] Food as reward, Restriction, Monitoring, Perceived responsibility for child feeding, Pressure to eat (Continuous); [underlined: CFP Definition:] Per CFQ; [underlined: CFP Assessment Method:] Child Feeding Questionnaire (CFQ); [underlined: Child age at initial exposure measurement:] 2–5 [Mean (SD): 3.8 (0.6)] y; [underlined: Outcome(s):] Growth, Body composition; [underlined: Outcome assessment method:] Height, weight, waist circumference measured by trained staff. Sex- and age-adjusted BMI z-scores calculated using WHO standard. Waist circumference (WC) compared with the 90th percentile of the Third National Health and Nutrition Examination Survey of Mexican American children.; [underlined: Age(s) at outcome assessment:] 3–6 y | [underlined: Change in BMIz from 2–5 y and 3–6 y, β]; Girls; [underlined: Food reward:] 0.306 p=0.04; [underlined: Restriction]: 0.337 p=0.03 | [underlined: BMIz @ 3–6 y, β]; [underlined: Food reward:] −0.011, p=0.86; [underlined: Pressure to eat:] −0.019, p=0.86; [underlined: Restriction]: −0.108, p=0.31; Monitoring: −0.085, p=0.44; Boys; [underlined: Food reward:] −0.018, p=0.89; [underlined: Restriction:] −0.019, p=0.90; [underlined: Pressure to eat:] 0.022, p=0.88; Monitoring: −0.241, p=0.17; Girls; [underlined: Food reward:] −0.208, p=0.16; [underlined: Pressure to eat]: −0.063, p=0.68; [underlined: Restriction:] −0.103, p=0.49; Monitoring: 0.130, p=0.39; [underlined: Change in BMI from 2–5 y and 3–6 y, β]; [underlined: Food reward:] 0.204, p=0.06; [underlined: Pressure to eat:] 0.039, p=0.71; [underlined: Restriction:] −0.129, p=0.32; Monitoring: 0.046, p=0.68; Boys; [underlined: Food reward:] 0.235, p=0.15; [underlined: Pressure to eat:] 0.078, p=0.62; [underlined: Restriction:] 0.011, p=0.95; Monitoring: −0.066, p=0.95; Girls; [underlined: Pressure to eat]: −0.002, p=0.99; Monitoring: 0.136, p=0.37; [underlined: Change in WC from 2–5 y and 3–6 y, β]; [underlined: Food reward:] 0.087, p=0.41; [underlined: Pressure to eat]: 0.003, p=0.98; [underlined: Restriction:] −0.005, p=0.48; Monitoring: 0.083, p=0.45; Boys; [underlined: Food reward:] 0.026, p=0.87; [underlined: Pressure to eat:] −0.017, p=0.91; [underlined: Restriction]: −0.017, p=0.92; Monitoring: 0.181, p=0.31; Girls; [underlined: Food reward:] 0.182, p=0.22; [underlined: Pressure to eat]: 0.005, p=0.98; [underlined: Restriction]: −0.178, p=0.23; Monitoring: 0.078, p=0.61 | [underlined: Key confounders accounted for:] Race and/or ethnicity; child sex; [underlined: Key confounders NOT accounted for]: SEP and/or parental or caregiver education; child's anthropometry at baseline; parental or caregiver BMI; [underlined: Model adjustments:] Other feeding practices; [underlined: Funding:] NR
Guivarch, 2023^27^; PCS, EDEN, France; Analytic N=1245; Power Analysis: NR; [underlined: Caregiver Characteristics]; - Mothers: 100%; - Age: 29.9 (4.7) y; - SEP and/or Education: (Maternal) < High school diploma: 22.1%, high school diploma: 17.7%, 2 y university degree: 23.8%, ≥ 5 y university degree: 36.5%; Household income (€/month): ≤ 1,500: 11.1%, 1,501–2,300: 29.7%, 2,301–3,000: 28.4%, >3,000: 30.8%; "higher SEP than the French population"; - Race and/or Ethnicity: NR; - BMI: Maternal pre-pregnancy BMI: 23.1 (4.3); Paternal pre-pregnancy BMI: 25.0 (3.5); - Other: Primiparous: 47.6%; [underlined: Child Characteristics]; - Female: 48%; - Baseline anthropometry: BMIZ @ 2 y: −0.4 (0.9); - Milk feeding practices: Any BF duration: <1 mo: 32.9%, 1 to <4 mo: 31.5%, ≥ 4 mo: 35.6%; [underlined: Primary aim:] First objective was to assess the associations between parental feeding practices in toddlerhood and children’s BMI up to 8 years. The second objective was to examine whether parental feeding practices may be considered as moderating or mediating factors in the associations between early and later child BMI. | [underlined: Exposures and Comparators:] Restriction for health, Restriction for weight, Pressure to eat, Using food to regulate child's emotion, Food as reward (Continuous (restriction and pressure); Low (< Median) vs High (≥ Median) (emotional feeding, food as reward)); [underlined: CFP Definition]: Per CFPQ; [underlined: CFP Assessment Method:] Comprehensive Feeding Practices Questionnaire (CFPQ); [underlined: Child age at initial exposure measurement:] 2 y; [underlined: Outcome(s):] Growth; [underlined: Outcome assessment method:] Parental report of weight and height at 4, 5, and 8 y. Growth curves calculated based on Jenss-Bayley growth curve model. BMI z-scores calculated using the International Obesity Task Force references.; [underlined: Age(s) at outcome assessment]: 4, 6, 8 y (reported as 4, 5, and 8 y) | [underlined: BMIz @ 4, 6, 8 y, β (95% CI)]; [underlined: Restriction for weight]; [underlined: BMIz @ 4 y:] 0.05 (0.01, 0.09), p=0.01; [underlined: BMIz @ 6 y:] 0.08 (0.02, 0.14), p=0.008; [underlined: BMIz @ 8 y:] 0.10 (0.03, 0.17), p=0.008; [underlined: High use of food as a reward,] Boys; [underlined: BMIz @ 4 y]: 0.08 (0.01, 0.15), p=0.03; [underlined: BMIz @ 6 y:] 0.12 (0.02, 0.22), p=0.02; [underlined: BMIz @ 8 y]: 0.14 (0.02, 0.26), p=0.02; [underlined: BMIz @ 6, 8 y, β (95% CI)]; [underlined: Restriction for health]; [underlined: BMIz @ 6 y:] 0.04 (0.00, 0.07), p=0.04; [underlined: BMIz @ 8 y:] 0.05 (0.01, 0.09), p=0.01 | [underlined: BMIz @ 4 y, β (95% CI)]; [underlined: Restriction for health] : 0.01 (−0.01, 0.04), p=0.20; [underlined: Pressure to eat]; [underlined: BMIz @ 4 y]: 0.00 (−0.03, 0.03), p=1.0; [underlined: BMIz @ 6 y]: 0.00 (−0.04, 0.04), p=1.0; [underlined: BMIz @ 8 y]: 0.00 (−0.06, 0.05), p=0.8; [underlined: High emotional feeding]; [underlined: BMIz @ 4 y:] 0.02 (−0.03, 0.07), p=0.4; [underlined: BMIz @ 6 y]: 0.03 (−0.04, 0.10), p=0.4; [underlined: BMIz @ 8 y:] 0.03 (−0.05, 0.11), p=0.5; [underlined: High use of food as a reward,] Girls; [underlined: BMIz @ 4 y]: −0.02 (−0.09, 0.05), p=0.6; [underlined: BMIz @ 6 y:] 0.00 (−0.10, 0.10), p=1.0; [underlined: BMIz @ 8 y:] 0.02 (−0.10, 0.14), p=0.8 | [underlined: Key confounders accounted for:] SEP and/or parental or caregiver education; child's anthropometry at baseline; child sex; parental or caregiver BMI; [underlined: Key confounders NOT accounted for:] Race and/or ethnicity; [underlined: Model adjustments:] Study center, maternal primiparity, age at delivery, maternal education level, household income, smoking status during pregnancy, parental BMI, child sex, preterm birth, any breastfeeding duration, 4-to-24-month appetite and 2 y BMIz score (baseline); [underlined: Funding:] Fondation pour la Recherche Médicale; French Ministry of Research; INSERM Human Nutrition National Research Program; Diabetes National Research Program; French Ministry of Health; French Agency for Environment Security; French National Institute for Population Health Surveillance; Paris‐ Sud University; French National Institute for Health Education; Nestlé; Mutuelle Générale de l'Education Nationale; French-speaking Association for the Study of Diabetes and Metabolism; National Agency for Research; National Institute for Research in Public Health
Papaioannou, 2023^14^; PCS, US; Analytic N=129; Power Analysis: NR; [underlined: Caregiver Characteristics]; - Mothers: 100%; - Age: 31.55 (6.60) y; - SEP and/or Education: > High school: 38%, High school or equivalent: 24%, Some college or more: 38%; Employed: 20.9%; Attending HeadStart: 100%; - Race and/or Ethnicity: Hispanic: 100%; - BMI: NR; - Other: Parent: Married: 58.9%, Never married: 14%, widowed/separated/divorced: 27.1%; Parent born in US: 17.8%, Born in Mexico: 63.5%, Born in Central America: 17.9%; Child Born in U.S: 96.9%; [underlined: Child Characteristics]; - Female: 54%; - Baseline anthropometry: Underweight (<5th percentile): 1.6, Healthy weight (5th to <85th percentile): 48.8% Overweight (85th to <95th percentile): 22.5% Obese (≥95th percentile): 27.1%; Pressure to eat: p<0.001, Authoritarian: p<0.05, Indulgent: p<0.05; - Milk feeding practices: NR; [underlined: Primary aim]: To examine the degree to which individual differences in children’s food motivation in the preschool years interacted with mothers’ feeding styles in predicting subsequent weight status in Hispanic children from low-income levels. | [underlined: Exposures and Comparators:] Restriction, Pressure to eat, Monitoring (Continuous); [underlined: CFP Definition:] Per CFQ; [underlined: CFP Assessment Method:] Child Feeding Questionnaire (CFQ); [underlined: Child age at initial exposure measurement:] 4–5 y (Mean (SD): 4.76 (0.46) y); [underlined: Outcome(s):] Growth; [underlined: Outcome assessment method:] Height and weight were measured by trained staff. Age- and gender-specific BMI z-scores were calculated using the CDC Reference Standards.; [underlined: Age(s) at outcome assessment:] 8.34 (0.71) y | [underlined: BMIz @ ~ 8 y, β (95% CI)]; Monitoring: −0.17 (−0.30, −0.04), p<0.01 | [underlined: BMIz @ ~ 8 y, β (95% CI)]; [underlined: Pressure to eat:] 0.02 (−0.11, 0.15), p≥0.05; [underlined: Restriction:] 0.15 (−0.02, 0.32), p≥0.05 | [underlined: Key confounders accounted for:] Race and/or ethnicity, SEP and/or parental or caregiver education, child's anthropometry at baseline; [underlined: Key confounders NOT accounted for:] Parental or caregiver BMI; [underlined: Model adjustments:] Child BMIz @ time 1, CFQ feeding practices, CFSQ feeding styles, highly motivated eating score, 3 feeding styles by highly motivated eating interactions; [underlined: Funding:] NICHD, USDA/ARS
Quah, 2019^16^; PCS, the Growing Up in Singapore Toward healthy Outcomes (GUSTO), Singapore; Analytic N=428; Power Analysis: NR; [underlined: Caregiver Characteristics]; - Mothers: 100%; - Age: 30.6 (5.3) y; - SEP and/or Education: None/primary/secondary: 28%, post−secondary/tertiary: 72%; - Race and/or Ethnicity: Child Ethnicity: Chinese: 47%, Malay: 32%, Indian: 21%; - BMI: BMI @ 15 wk gestation: 24.1 (5.0); - Other: Primiparous: 44%, Multiparous: 56%; [underlined: Child Characteristics]; - Female: 49%; - Baseline anthropometry: BMIZ @ 4 y: 0.22 (1.3); Overweight status (> + 2 z-score)@ 4 y: 7.8%; Normal weight: 92.2%; NR differences bw groups; - Milk feeding practices: Never BF: 3.6%, BF for <6mo: 86.4%, BF for >6 mo: 10%; [underlined: Primary aim:] To examine bidirectional associations between the 12 different maternal feeding practices (measured at 5 y) subscales and child BMI (measured at 4 and 6y) and to test the strength of bidirectional associations for feeding practices that are significantly associated with BMI. | [underlined: Exposures and Comparators:] Encouraging balance/variety, Healthy environment, Teaching about nutrition, Child involvement, Monitoring, Restriction for weight control, Restriction for health, Pressure, Emotional regulation, Child control, Food as reward (Continuous); [underlined: CFP Definition:] Per CFPQ; [underlined: CFP Assessment Method:] Comprehensive Feeding Practices Questionnaire (CFPQ); [underlined: Child age at initial exposure measurement:] 4.9 (0.2) y; [underlined: Outcome(s):]; [underlined: Outcome assessment method:] Child’s weights and heights were measured by trained staff and used to calculated BMI. Age and sex-adjusted BMI z-sores were calculated using the WHO Child Growth Standards 2007 in the WHO Anthro software. Child overweight/obese were categorized using WHO cut-offs of above +2 z-score for children aged 4, and +1 z-score for children aged 6 years.; [underlined: Age(s) at outcome assessment:] 6 y | [underlined: BMIz @ 6 y, β (95% CI)]; [underlined: Restriction for weight control:] 0.02 (0.002, 0.03), p=0.024 | [underlined: BMIz @ 6 y, β (95% CI)]; [underlined: Restriction for health]: 0.056 (0.005, 0.11), p=0.030; [underlined: Emotional regulation:] 0.007 (−0.05, 0.06), p=0.811; [underlined: Child control:] −0.02 (−0.07, 0.02), p=0.252; [underlined: Food as reward]: −0.01 (−0.07, 0.05), p=0.690; [underlined: Pressure:] 0.01 (−0.01, 0.03), p=0.300; Modelling: −0.02 (−0.06, 0.02), p=0.351; Encouraging balance and variety: −0.05 (−0.10, 0.003), p=0.048; Healthy environment: 0.02 (−0.03, 0.07), p=0.419; Teaching about nutrition: −0.02 (−0.08, 0.04), p=0.320; Child involvement: −0.05 (−0.11,−0.001), p= 0.045; Monitoring: 0.05 (0.009, 0.08), p= 0.013 | [underlined: Key confounders accounted for:] SEP and/or parental or caregiver education; race and/or ethnicity; child's anthropometry at baseline; child sex; parental or caregiver BMI; [underlined: Key confounders NOT accounted for]: None; [underlined: Model adjustments:] CFPQ assessment, BMI during early pregnancy (<14 weeks), child birth order, duration of breastfeeding, ethnicity, and maternal education, BMIz at 5 y (model with restriction for weight control and pressure only); [underlined: Funding:] Singapore National Research Foundation, Translational and Clinical Research (TCR) Flagship Programme; Singapore Institute for Clinical Sciences; Agency for Science, Technology and Research (A∗STAR), Singapore; the Singapore Institute for Clinical Sciences, A∗STARand Nestec.
Bergmeier, 2014^3^; PCS, Australia; Analytic N=201; Power Analysis: NR; [underlined: Caregiver Characteristics]; - Mothers: 100%; - Age: 36.11 (4.09) y; - SEP and/or Education: Bachelor's degree: 67.7%; Family income <A$45,000: 6.4%, A$45,001-A$85,000: 31.5%, A$85,001−A$145,000: 44.5%, > A$145,001: 17.6%; - Race and/or Ethnicity: NR; - BMI: Maternal BMI: 25.03 (4.54); Underweight; 1.9%, normal weight: 52.9%, overweight: 35.2%, obese: 10%; - Other: Born in Australia: 81.9%, Europe: 8.9%, New Zealand: 3.4%; [underlined: Child Characteristics]; - Female: 58%; - Baseline anthropometry: Underweight: 16%, Healthy weight: 71%, Overweight: 10%, Obese: 3%; NR differences bw groups; - Milk feeding practices: NR; [underlined: Primary aim:] To examine cross-sectional and prospective associations between child temperament, maternal feeding, maternal parenting styles, mother–child interaction, preschoolers’ eating behaviors and BMI | [underlined: Exposures and Comparators:] Restriction, pressure to eat, monitoring (Continuous); [underlined: CFP Definition:] Per CFQ; [underlined: CFP Assessment Method:] Child Feeding Questionnaire (CFQ); [underlined: Child age at initial exposure measurement:] 2–5 [Mean (SD): 2.92 (0.75)] y; [underlined: Outcome(s):] Growth; [underlined: Outcome assessment method:] Mothers reported child’s height and weight measurements. BMI z-scores were calculated. BMI cut-off points developed by CDC were used to classify children as normal weight, overweight or obese.; [underlined: Age(s) at outcome assessment]: ~ 4 y | | [underlined: BMIz @ ~4y, β]; [underlined: Restriction:] 0.01, NS; [underlined: BMIz @ ~4y, β]; [underlined: Pressure to eat:] 0.02, NS; BMIz @ ~4y, β; Monitoring: −0.01, NS | [underlined: Key confounders accounted for:] SEP and/or parental or caregiver education; parental or caregiver BMI; [underlined: Key confounders NOT accounted for:] Race and/or ethnicity; child's anthropometry at baseline; child sex; [underlined: Model adjustments:] Maternal educational achievement, family income, and maternal BMI, child BMIz; [underlined: Funding:] Australian Research Council Discovery
Bergmeier, 2015^20^; PCS, Australia; Analytic N=72; Power Analysis: NR; [underlined: Caregiver Characteristics]; - Mothers: 100%; - Age: NR; - SEP and/or Education: Tertiary qualification: 71%; Family income < A$45,000: 6%, A$45,001 – $85,000: 23%, A$85,001 – $145,001: 57%, > A$145,001: 14%; - Race and/or Ethnicity: NR; - BMI: Healthy weight: 46%, Overweight: 40%, Obese: 14%; - Other: Born in Australia: 85% Europe: 8%, New Zealand: 2.5%, South Africa: 2.5%, North America: 1%, Asia: 1%; [underlined: Child Characteristics]; - Female: 54%; - Baseline anthropometry: Underweight: 4%, Healthy weight: 73%, Overweight: 22%, Obese: 1%, NR differences bw groups; - Milk feeding practices: NR; [underlined: Primary aim:] 1) To compare reported and observed maternal feeding at baseline and after 12 month. 2)To assess the relations between maternal and child factors at baseline (concern about child weight, parenting styles, child temperament, child BMI) and reported and observed maternal feeding practices at baseline and 12-month follow-up. 3) To evaluate the prospective associations that maternal and child obesity risk factors at baseline (controlling feeding practices, concern about child weight, parenting styles, child temperament, child BMI and child eating) have with child eating and child BMI at 12-month follow-up. | [underlined: Exposures and Comparators:] Pressure to eat, restriction (Continuous); [underlined: CFP Definition:] As per CFQ and FMCS (4 subscales used to code verbal and nonverbal maternal pressure to eat and restriction feeding practices); [underlined: CFP Assessment Method:] Child Feeding Questionnaire (CFQ) and Family Mealtime Coding System; [underlined: Child age at initial exposure measurement:] 2–5 [Mean (SD): 3.09 (0.75)] y; [underlined: Outcome(s):] Growth; [underlined: Outcome assessment method:] Height and weight were collected by trained research staff. Child BMI z-scores were computed according to the CDC criteria and children were classified as normal weight, overweight, or obese.; [underlined: Age(s) at outcome assessment:] ~4 y | [underlined: BMIz @ ~4 y, β]; [underlined: Observed restriction:] −0.18, p < 0.05 | [underlined: BMIz @ ~4 y, (data not reported)]; [underlined: Reported pressure to eat:] p≥0.05; [underlined: Reported restriction]: p≥0.05; [underlined: Observed pressure to eat:] p≥0.05 | [underlined: Key confounders accounted for:] Child's anthropometry at baseline; [underlined: Key confounders NOT accounted for:] SEP and/or parental or caregiver education; race and/or ethnicity; child sex; parental or caregiver BMI; [underlined: Model adjustments:] Child BMIz at baseline, maternal parenting control and concern about child weight, child difficult temperament, child food fussiness at baseline, child enjoyment of food at baseline; [underlined: Funding:] Australian Research Council Discovery
Campbell, 2010^22^; PCS, Health, Eating and Play Study, Australia; Analytic N=392; Power Analysis: NR; [underlined: Caregiver Characteristics]; - Females: 50%; - Age: NR; - SEP and/or Education: High: 45%, Medium: 34%, Low: 19%; - Race and/or Ethnicity: NR; - BMI: Maternal BMI: 5–6 y:25.5 (5.5), 10–12 y: 24.4 (4.8); - Other: NA; [underlined: Child Characteristics]; - Female: NR; - Baseline anthropometry: BMIZ: 5–6 y: 0.6 (0.9), 10–12 y: 0.4 (0.9), NR differences bw groups; - Milk feeding practices: NR; [underlined: Primary aim:] To describe associations between parental use of feeding restriction at baseline and BMI z-scores at 3-year follow-up in a sample of children and a sample of adolescents. | [underlined: Exposures and Comparators:] Restriction (Continuous); [underlined: CFP Definition:] Per CFQ; [underlined: CFP Assessment Method:] Caregiver Feeding Questionnaire (CFQ); [underlined: Child age at initial exposure measurement:] 5–6 y, 10–12 y; [underlined: Outcome(s):] Growth; [underlined: Outcome assessment method:] Height and weight were measured by trained staff. Body mass index was calculated and converted to BMI z-scores using CDC growth reference.; [underlined: Age(s) at outcome assessment:] 8–9, 13–15 y | [underlined: BMIz @ 8–9 y, β (95% CI)]; [underlined: Restriction @ 5–6 y]: −0.013 (−0.025, −0.001), p=0.04 | | [underlined: Key confounders accounted for:] SEP and/or parental or caregiver education; child's anthropometry at baseline; child sex; parental or caregiver BMI; [underlined: Key confounders NOT accounted for:] Race and/or ethnicity; [underlined: Model adjustments:] Child baseline BMIz, maternal baseline BMI, maternal education level and child sex; [underlined: Funding:] NR
Faith, 2004^5^; PCS, Infant Growth Study, US; Analytic N=57; Power Analysis: Underpowered to detect weak associations (r=0.1–0.2); [underlined: Caregiver Characteristics]; - Mothers: 88%, Fathers: 12%; - Age: NR; - SEP and/or Education: NR; - Race and/or Ethnicity: White: 100%; - BMI: Mother's BMI (high risk): 30.3 (4.2), Mother's BMI (low risk): 19.5 (1.1), Father's BMI (high risk): 27.6 (5.9), Father's BMI (low risk): 27.9 (2.9); - Other: NA; [underlined: Child Characteristics]; - Female: NR; - Baseline anthropometry: BMIz @ 5 y: 0.30 (1.2), Monitoring (Low Risk): p<0.05; - Milk feeding practices: NR; [underlined: Primary aim]: To examine whether 1) Parental feeding attitudes and styles stable for 2 years, 2) Parental feeding attitudes and styles associated with child BMI z scores cross-sectionally and prospectively, and whether these associations depend on child obesity risk status, and 3) Parental feeding attitudes and styles predict subsequent child BMI z scores, when controlling for the child’s prior BMI z score | [underlined: Exposures and Comparators:] Pressure to eat, Restriction, Monitoring (Continuous); [underlined: CFP Definition:] Per CFQ; [underlined: CFP Assessment Method]: Child Feeding Questionnaire (CFQ); [underlined: Child age at initial exposure measurement:] 5 y; [underlined: Outcome(s):] Growth; [underlined: Outcome assessment method]: Child weight and height was measured, and BMI was computed and converted to z-scores.; [underlined: Age(s) at outcome assessment:] 7 y | [underlined: BMIz @ 7 y, β]; [underlined: Restriction (high risk):] 0.39, p≤0.05; [underlined: Pressure to eat (high risk):] −0.35, p≤0.05; Monitoring (low risk): −0.33, p≤0.05 | [underlined: BMIz @ 7 y, β]; [underlined: Restriction (low risk):] 0.07, p>0.05; [underlined: Pressure to eat (low risk):] – 0.11, p>0.05; Monitoring (high risk): 0.10, p>0.05 | [underlined: Key confounders accounted for:] Child's anthropometry at baseline; parental or caregiver BMI, child sex; [underlined: Key confounders NOT accounted for:] SEP and/or parental or caregiver education; race and/or ethnicity;; [underlined: Model adjustments:] Caregiver feeding styles (restriction, monitoring, pressure to eat), Child BMIz @ 3 y; [underlined: Funding:] NIH; General Clinical Research Center; the Nutrition and Growth Laboratory of Children’s Hospital of Philadelphia
Gregory, 2010^7^; PCS, The Child and Family Health Study, Australia; Analytic N=106; Power Analysis: NR; [underlined: Caregiver Characteristics]; - Mothers: 100%; - Age: 35 (5.2) y; - SEP and/or Education: Tertiary education: 60%; - Race and/or Ethnicity: NR; - BMI: Overweight: 51%; - Other: Married/de facto relationship: 87%; [underlined: Child Characteristics]; - Female: 51%; - Baseline anthropometry: Overweight/obese: 15%; Pressure to eat: p<0.05; - Milk feeding practices: NR; [underlined: Primary aim:] To examine the extent to which maternal feeding practices prospectively predict the development of eating behavior and BMI in preschool-aged children. | [underlined: Exposures and Comparators:] Pressure to eat, Restriction, Monitoring, Modeling (Continuous); [underlined: CFP Definition:]; - Pressure to eat, Restriction, Monitoring - Per CFQ; - Modeling of eating healthy foods; [underlined: CFP Assessment Method:] Child Feeding Questionnaire (CFQ), 3-items (modeling); [underlined: Child age at initial exposure measurement:] 2–4 [Mean (SD): 3.3 (0.8)] y; [underlined: Outcome(s):] Growth; [underlined: Outcome assessment method:] Mothers reported on their child's age, gender, weight and height. Child BMI z-scores were calculated per CDC 2000 growth charts; [underlined: Age(s) at outcome assessment:] 4.3 y | | [underlined: BMIz @~4 y, β Pressure to eat]: p≥0.05; [underlined: Restriction:] p≥0.05 Monitoring: p≥0.05 Modeling: p≥0.05 | [underlined: Key confounders accounted for:] SEP and/or parental or caregiver education; child sex; parental or caregiver BMI, child's anthropometry at baseline; [underlined: Key confounders NOT accounted for:] Race and/or ethnicity;; [underlined: Model adjustments:] Baseline BMIZ, Child age and gender, maternal age, Maternal BMI, education; [underlined: Funding:] National Heart Foundation Australia
Jansen, 2014^12^; PCS, Generation R (fetal life onwards), Netherlands; Analytic N=4166; Power Analysis: NR; [underlined: Caregiver Characteristics]; - Mothers: 100%; - Age: NR; - SEP and/or Education: <3 y of secondary school: 8.2%, Secondary: 26.8%, Higher vocational: 29.7%, Academic: 35.3%; - Race and/or Ethnicity: Dutch: 66.5%, Other Western: 9.8%, Non-Western: 23.7%; - BMI: 24.5 (6 4.1); - Other: NA; [underlined: Child Characteristics]; - Female: 50%; - Baseline anthropometry: BMI SD score @ 2y: 0.22 (1.0), BMI SD score @ 4y: 0.20 (0.87); Restriction & Pressure to eat: p<0.001; - Milk feeding practices: NR; [underlined: Primary aim:] To examine longitudinal relations between selected feeding practices (pressure, restriction, monitoring) and early childhood BMI in a large population-based cohort. | [underlined: Exposures and Comparators:] Pressure to eat, Restriction, Monitoring, Pressuring feeding (Continuous); [underlined: CFP Definition:]; - Pressure to eat, restriction, monitoring - per CFQ; - Pressuring feeding if 2-y-old child would not eat measured using 5 self-report items; [underlined: CFP Assessment Method:] Child Feeding Questionnaire (CFQ), 5-items (Pressuring feeding); [underlined: Child age at initial exposure measurement:] Pressuring feeding: 2 y, CFQ: 4.1 (0.1) y; [underlined: Outcome(s):] Weight status; [underlined: Outcome assessment method:] Children’s weights and heights were measured by trained staff using standardized procedures. BMI was calculated, and age- and sex-specific BMI SD scores were calculated using the Dutch reference population.; [underlined: Age(s) at outcome assessment:] 4, 6 y | [underlined: BMI SD @ 6 y, β (95% CI)]; [underlined: Pressure to eat:] −0.02 (−0.04, −0.01), p=0.01 | [underlined: BMI SD @ 4 y, β (95% CI)]; [underlined: Pressuring feeding:] −0.01 (−0.04, 0.01), p=0.32; [underlined: BMI SD @ 6 y, β (95% CI)]; [underlined: Restriction:] 0.01 (−0.01, 0.03), p=0.25; Monitoring: −0.01 (−0.04, 0.02), p=0.40 | [underlined: Key confounders accounted for:] SEP and/or parental or caregiver education; race and/or ethnicity; child's anthropometry at baseline; child sex; parental or caregiver BMI; [underlined: Key confounders NOT accounted for:] None; [underlined: Model adjustments:] Child sex, age at CFQ assessment and national origin, maternal BMI, maternal education, child BMI at baseline (2 y or 4 y); [underlined: Funding:] Nestlé Nutrition (Nestec Ltd), Metagenics Inc
Karp, 2014^13^; PCS, US; Analytic N=77; Power Analysis: NR; [underlined: Caregiver Characteristics]; - Mothers: 93.5%; - Age: 31.6 (5.6) y; - SEP and/or Education: <HS: 65%, ≥HS <College: 30%, ≥College: 5.2%; - Race and/or Ethnicity: Latino: 100%; - BMI: BMI: 29.73 (5.65); - Other: Country of origin: Mexico: 84.4%, Other central American country: 10.4%, US: 5.2%; Acculturation (low): 97.4%; [underlined: Child Characteristics]; - Female: 52%; - Baseline anthropometry: BMI %, median (25th and 75th IQR): 81.9 (51.3, 92.8), NS difference bw groups; - Milk feeding practices: NR; [underlined: Primary aim:] To examine the relationships between parental patterns regarding child feeding and child Body Mass Index (BMI) percentile in Latino parent-preschooler dyads participating in a clinical trial. | [underlined: Exposures and Comparators:] Restriction, Monitoring (Continuous); [underlined: CFP Definition:] Per CFQ CFP Assessment Method: Child Feeding Questionnaire (CFQ); [underlined: Child age at initial exposure measurement:] 2–6 [Mean (SD): 4.14 (0.87)] y; [underlined: Outcome(s):] Growth; [underlined: Outcome assessment method:] Child BMI was calculated from height and weight measured using a stadiometer and a a calibrated digital scale, respectively. BMI percentile for age and gender was calculated using the CDC calculator and corresponding weight categorization (normal: ≥5% but <85%; overweight: ≥85% but <95%; obese: ≥95%) was assigned.; [underlined: Age(s) at outcome assessment:] ~ 4 y | | [underlined: BMI % 3 mo change, r Change in Restriction]: 0.12, p=0.327 Change in Monitoring: 0.10, p=0.400 | [underlined: Key confounders accounted for:] None; [underlined: Key confounders NOT accounted for:] SEP and/or parental or caregiver education; race and/or ethnicity; child's anthropometry at baseline; child sex; parental or caregiver BMI; [underlined: Model adjustments:] None; [underlined: Funding]: Project Diabetes Implementation, State of Tennessee
Chong, 2017^23^; PCS, Avon Longitudinal Study of Parents and Children (ALSPAC), UK; Analytic N=7312; Power Analysis: NR; [underlined: Caregiver Characteristics]; - Mothers: 100%; - Age: 29.16 (4.51) y; - SEP and/or Education: Maternal education: None/CSE/vocational: 21.7%, O level: 35.7%, A level: 26.6%, Degree: 16.1%; Parental highest social class: I/ii (highest): 60.1%. III: 35.5%, IV/V (lowest class): 4.4%; Had financial difficulty: 7.9%; Home ownership, rented/other: 16.7%; - Race and/or Ethnicity: Non-White ethnicity: 3.9%; - BMI: Maternal BMI: 22.92 (3.73); - Other: Number of other children: None: 45.4%, 1: 37.1%, 2: 13.7%, 3: 3.0%, ≥4: 0.8%; [underlined: Child Characteristics]; - Female: 49%; - Baseline anthropometry: Birth weight z-score: 0.13 (0.99), NR differences bw groups; - Milk feeding practices: NR; [underlined: Primary aim:] To investigate the associations between parentals food-choice control and food to soothe at 3.5 y on children’s BMI z-scores at 7 and 15 y and fat mass at 15 y. | [underlined: Exposures and Comparators:] Parental food choice control; food to soothe (Food-choice control: Choice of few, Parent decides vs Can choose any (ref); Food to soothe: Infrequent, never, vs frequent (ref)); [underlined: CFP Definition:] Food choice control: Mother deciding what child will eat; Food to soothe: Frequency of using sweets and other foods to stop crying or fussing; [underlined: CFP Assessment Method:] Questionnaire (single item); [underlined: Child age at initial exposure measurement:] 3.5 y; [underlined: Outcome(s):] Growth, Body composition; [underlined: Outcome assessment method:] Height and weight measured by trained researchers and converted to BMI z-scores based on British 1990 growth reference. Total fat mass assessed using DXA.; [underlined: Age(s) at outcome assessment:] 7, 15 y | [underlined: BMIz @ 15 y, β (95% CI)]; Choice of few vs. Can choose any (ref): −0.11 (−0.21, −0.01); Parent decides vs. Can choose any (ref): −0.12 (−0.23, −0.01); [underlined: Fat mass (kg) @ 15 y, β (95% CI)]; Choice of few vs. Can choose any (ref): −1.08 (−1.89, −0.32); Parent decides vs. Can choose any (ref): −1.46 (−2.26, −0.66) | [underlined: BMIz @ 7 y, β (95% CI)]; Choice of few vs. Can choose any (ref): −0.07 (−0.15, 0.02); Parent decides vs. Can choose any (ref): −0.08 (−0.16, 0.01); [underlined: Food to soothe]; [underlined: Infrequent vs. Frequent (ref):] −0.03 (−0.10, 0.05); [underlined: Never vs. Frequent (ref):] −0.03 (−0.11, 0.05); [underlined: BMIz @ 15 y, β (95% CI)]; [underlined: Food to soothe]; [underlined: Infrequent vs. Frequent (ref)]: 0.04 (−0.05, 0.12); [underlined: Never vs. Frequent (ref):] 0.01 (−0.08, 0.10); [underlined: Fat mass (kg) @ 15 y, β (95% CI)]; [underlined: Food to soothe]; [underlined: Infrequent vs. Frequent (ref):] −0.03 (−0.64, 0.71); [underlined: Never vs. Frequent (ref):] −0.12 (−0.58, 0.84) | [underlined: Key confounders accounted for:] SEP and/or parental or caregiver education; race and/or ethnicity; child sex; parental or caregiver BMI; [underlined: Key confounders NOT accounted for:] Child's anthropometry at baseline; [underlined: Model adjustments]: child temperament at 6 mo, child's dietary patterns at age 3 y, maternal education, sole parenting, financial difficulties, social class, home ownership, maternal age, birth weight z-score, alcohol, smoking, maternal BMI, crowding index, maternal depression, number of other children, ethnicity, child not eaten enough, child refuse right food, child choosy with food, child overeaten, difficult to establish eating routine, hours of television watching, age, sex, height (fat mass only), parental use of food to soothe (food-choice control only), parental food-choice control (food to soothe only); [underlined: Funding:] The UK Medical Research Council; Welcome Trust; University of Bristol
McPhie, 2012^29^; PCS, Australia; Analytic N=117; Power Analysis: Power analysis [n=196–329] for a power of 0.08 for SEM with df range from 30–36; [underlined: Caregiver Characteristics]; - Mother: 100%; - Age: 35.84 (3.93) y; - SEP and/or Education: Bachelor degree: 77%; Family income >$85,001: 70.9 %; - Race and/or Ethnicity: NR; - BMI: Maternal BMI: 24.56 (3.87); - Other: Maternal country of birth, Australia/New Zealand: 74.4%, Europe: 21.2%, Asia: 0.9%, Other: 4.5%; Multiparous: 61.5%; [underlined: Child Characteristics]; - Female: 54%; - Baseline anthropometry: Not overweight/obese (girls): 89%, Overweight/obese (girls): 11%, Not overweight/obese (boys): 90%, Overweight/obese (boys): 9%,; - Milk feeding practices: NR; [underlined: Primary aim:] To prospectively evaluate maternal child-feeding practices, parenting style and mother–child interactions as predictors of child-eating behaviours, food habits and weight. | [underlined: Exposures and Comparators:] Restriction, Pressure to eat (Continuous); [underlined: CFP Definition:] Per CFQ; [underlined: CFP Assessment Method:] Child Feeding Questionnaire (CFQ); [underlined: Child age at initial exposure measurement:] 2.80 (0.68) y; [underlined: Outcome(s):] Weight status; [underlined: Outcome assessment method:] Height and weight measurements were reported by mother. BMIz for age and sex were calculated using the CDC Growth Reference Curves (2000). Child BMIz change variable was created by calculating the difference in child BMIz from baseline to follow-up.; [underlined: Age(s) at outcome assessment:] 3.91 (0.73) y | [underlined: BMIz 1 y change, β]; [underlined: Pressure to eat:] 0.18, p<0.05 | [underlined: BMIz 1 y change, β]; [underlined: Restriction:] NS, p>0.05 | [underlined: Key confounders accounted for:] SEP and/or parental education; [underlined: Key confounders NOT accounted for:] Race and/or ethnicity; child sex; parental or caregiver BMI; child's anthropometry at baseline; [underlined: Model adjustments:] Maternal warmth/control, mother-child dysfunctional interaction, family income, child unhealthy food habits, child fruit/vegetable habits; [underlined: Funding:] NR

a Abbreviations: BMI: Body Mass Index; BMIz: Body Mass Index Z score; CFP: Caregiver feeding practice; CFQ: Child Feeding Questionnaire; CFPQ: Comprehensive Feeding Practices Questionnaire; NR: Not Reported; NA: Not applicable; Socioeconomic position

b Food parenting practices that fall within this bucket are underlined.

Table 15 Risk of bias for observational studies examining controlling feeding practices and growth, body composition, and risk of obesity^a^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Afonso, 2016^1^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Bergmeier, 2014^3^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | HIGH | SOME CONCERNS | SOME CONCERNS | HIGH
Bergmeier, 2015^20^ (Exposure: Home observations) | HIGH | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS | HIGH
Bergmeier, 2015^20^ (Exposure: self-reported) | HIGH | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | HIGH
Bergmeier, 2016^19^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | LOW | HIGH | HIGH
Berkowitz, 2010^21^ | HIGH | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Campbell, 2010^22^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Chong, 2017^23^ | SOME CONCERNS | HIGH | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Derks, 2017^24^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Eichler, 2019^4^ | HIGH | SOME CONCERNS | LOW | LOW | HIGH | LOW | LOW | HIGH
Faith, 2004^5^ | HIGH | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | HIGH
Farrow, 2018^25^ | SOME CONCERNS | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Fulkerson, 2013^26^ | SOME CONCERNS | SOME CONCERNS | LOW | SOME CONCERNS | LOW | LOW | SOME CONCERNS | HIGH
Gable, 2007^6^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Gregory, 2010^7^) | SOME CONCERNS | SOME CONCERNS | LOW | LOW | HIGH | SOME CONCERNS | SOME CONCERNS | HIGH
Gubbels, 2011^8^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | HIGH
Guivarch, 2023^27^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | SOME CONCERNS | LOW | HIGH
Hughes, 2016^10^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Hughes, 2021^11^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Jansen, 2014^12^ (Exposure: Pressuring to eat) | LOW | HIGH | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Jansen, 2014^12^ (Exposure: Restriction) | LOW | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Jansen, 2020^28^ | LOW | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Karp, 2014^13^ | VERY HIGH | SOME CONCERNS | LOW | HIGH | LOW | LOW | SOME CONCERNS | VERY HIGH
McPhie, 2012^29^ | HIGH | SOME CONCERNS | LOW | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | HIGH
Papaioannou, 2023^14^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Power, 2021^35^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Quah, 2019^16^ | LOW | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Rhee, 2009^30^ | SOME CONCERNS | HIGH | LOW | LOW | LOW | LOW | SOME CONCERNS | HIGH
Rodgers, 2013^17^ | VERY HIGH | SOME CONCERNS | LOW | LOW | HIGH | SOME CONCERNS | SOME CONCERNS | VERY HIGH
Rodgers, 2013^31^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Souto-Gallardo, 2020^18^ | HIGH | SOME CONCERNS | LOW | LOW | LOW | LOW | LOW | HIGH

a Possible ratings of low, some concerns, high, very high, no information, or not applicable were determined using the "Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)" tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602. ) *Low risk of bias except for concerns about uncontrolled confounding.

Table 16 Evidence examining the relationship between autonomy supportive feeding practices and growth, body composition and risk of obesity ^a^,^b^

Study and Population Characteristics | Intervention/Exposure and Comparator, Outcome | Significant Results | Non-Significant Results | Confounders, Model Adjustments, Funding
Chong, 2017^23^; PCS, Avon Longitudinal Study of Parents and Children (ALSPAC), UK; Analytic N=7312; Power Analysis: NR; [underlined: Caregiver Characteristics]; - Mothers: 100%; - Age: 29.16 (4.51) y; - SEP and/or Education: Maternal education: None/CSE/vocational: 21.7%, O level: 35.7%, A level: 26.6%, Degree: 16.1%; Parental highest social class: I/ii (highest): 60.1%. III: 35.5%, IV/V (lowest class): 4.4%; Had financial difficulty: 7.9%; Home ownership, rented/other: 16.7%; - Race and/or Ethnicity: Non-White ethnicity: 3.9%; - BMI: Maternal BMI: 22.92 (3.73); - Other: Number of other children: None: 45.4%, 1: 37.1%, 2: 13.7%, 3: 3.0%, ≥4: 0.8%; [underlined: Child Characteristics]; - Female: 49%; - Baseline anthropometry: Birth weight z-score: 0.13 (0.99), NR differences bw groups; - Milk feeding practices: NR; [underlined: Primary aim:] To investigate the associations between parentals food-choice control and food to soothe at 3.5 y on children’s BMI z-scores at 7 and 15 y and fat mass at 15 y. | [underlined: Exposures and Comparators:] Parental food choice control; food to soothe (Food-choice control: Choice of few, Parent decides vs Can choose any (ref); Food to soothe: Infrequent, never, vs frequent (ref)); [underlined: CFP Definition:] Food choice control: Mother deciding what child will eat; Food to soothe: Frequency of using sweets and other foods to stop crying or fussing; [underlined: CFP Assessment Method]: Questionnaire (single item); [underlined: Child age at initial exposure measurement]: 3.5 y; [underlined: Outcome(s):] Growth, Body composition; [underlined: Outcome assessment method]: Height and weight measured by trained researchers and converted to BMI z-scores based on British 1990 growth reference. Total fat mass assessed using DXA.; [underlined: Age(s) at outcome assessment:] 7, 15 y | [underlined: BMIz @ 15 y, β (95% CI)]; [underlined: Choice of few vs. Can choose any (ref):] −0.11 (−0.21, −0.01); [underlined: Parent decides vs. Can choose any (ref):] −0.12 (−0.23, −0.01); [underlined: Fat mass (kg) @ 15 y, β (95% CI) Choice of few vs. Can choose any (ref):] −1.08 (−1.89, −0.32); [underlined: Parent decides vs. Can choose any (ref):] −1.46 (−2.26, −0.66) | [underlined: BMIz @ 7 y, β (95% CI)]; [underlined: Choice of few vs. Can choose any (ref):] −0.07 (−0.15, 0.02); [underlined: Parent decides vs. Can choose any (ref):] −0.08 (−0.16, 0.01); Food to soothe; Infrequent vs. Frequent (ref): −0.03 (−0.10, 0.05); Never vs. Frequent (ref): −0.03 (− 0.11, 0.05); [underlined: BMIz @ 15 y, β (95% CI)]; Food to soothe; Infrequent vs. Frequent (ref): 0.04 (−0.05, 0.12); Never vs. Frequent (ref): 0.01 (− 0.08, 0.10); [underlined: Fat mass (kg) @ 15 y, β (95% CI)]; Food to soothe; Infrequent vs. Frequent (ref): −0.03 (−0.64, 0.71); Never vs. Frequent (ref): −0.12 (− 0.58, 0.84) | [underlined: Key confounders accounted for:] SEP and/or parental or caregiver education; race and/or ethnicity; child sex; parental or caregiver BMI; [underlined: Key confounders NOT accounted for:] Child's anthropometry at baseline; [underlined: Model adjustments]: child temperament at 6 mo, child's dietary patterns at age 3 y, maternal education, sole parenting, financial difficulties, social class, home ownership, maternal age, birth weight z-score, alcohol, smoking, maternal BMI, crowding index, maternal depression, number of other children, ethnicity, child not eaten enough, child refuse right food, child choosy with food, child overeaten, difficult to establish eating routine, hours of television watching, age, sex, height (fat mass only), parental use of food to soothe (food-choice control only), parental food-choice control (food to soothe only); [underlined: Funding:] The UK Medical Research Council; Wellcome Trust; University of Bristol
Faith, 2013^32^; PCS, National Longitudinal Study of Youth (NLSY), US; Analytic N=618; Power Analysis: NR; [underlined: Caregiver Characteristics]; - Mothers: 100%; - Age: ~25 y; - SEP and/or Education: NR; - Race and/or Ethnicity: Child race/ethnicity: Non-Hispanic/Non-African American: ~39%, African American: ~34%, Hispanic: ~27%; - BMI: ~24; - Other: NA; [underlined: Child Characteristics]; - Female: 49%; - Baseline anthropometry: BMI @ baseline: ~15.1, BMIZ @ baseline: ~0.50, BMI% @ baseline: ~37, NR differences bw groups; - Milk feeding practices: NR; [underlined: Primary aim]: To test whether poorer division of responsibility feeding predicts childhood overweight/obesity onset over 10 years | [underlined: Exposures and Comparators:] Food choice (Lower vs High choice); [underlined: CFP Definition]: Food Choice: how much choice child is allowed in deciding what foods child eats at breakfast and lunch; [underlined: CFP Assessment Method]: Questionnaire (Single item); [underlined: Child age at initial exposure measurement:] 1.8–6.9 y (Mean: ~4 y); [underlined: Outcome(s):] Growth, Weight status; [underlined: Outcome assessment method:] Height and weight measured by trained staff. Sex- and age-specific BMI z-scores and percentiles based on CDC growth charts.; Overweight/obesity defined as ≥85th %tile; [underlined: Age(s) at outcome assessment:] 4–9 y (2 y follow-up), 8–13 y (6 y follow−up), 10–15 y (8 y follow-up), 12–17 y (10 y follow-up) | | [underlined: Food choice (Lower vs higher (ref))]; [underlined: BMIz @ 10 y follow-up, β (SE)]; Girls: 0.00 (0.06), p=0.96; Boys: −0.05 (0.07), p=0.47; [underlined: Food choice (Lower vs higher (ref))]; [underlined: Overweight/obesity, OR (CI)]; Girls; [underlined: @ 2 y follow-up]: 0.61 (0.25, 1.50), p>0.05; [underlined: @ 6 y follow-up]: 0.71 (0.33, 1.54), p>0.05; [underlined: @ 8 y follow-up:] 0.84 (0.34, 2.03), p>0.05; [underlined: @ 10 y follow-up:] 1.40 (0.44, 4.44), p>0.05; Boys; [underlined: @ 2 y follow-up]: 0.60 (0.19, 1.92), p>0.05; [underlined: @ 6 y follow-up:] 0.80 (0.36, 1.79), p>0.05; [underlined: @ 8 y follow-up]: 0.73 (0.30, 1.81), p>0.05; [underlined: @ 10 y follow-up]: 0.30 (0.03, 2.75), p>0.05 | [underlined: Key confounders accounted for:]; SEP and/or parental or caregiver education; race and/or ethnicity; child sex; parental or caregiver BMI; [underlined: Key confounders NOT accounted for:] child's anthropometry at baseline; [underlined: Model adjustments]: Maternal obesity, maternal age, maternal education, child race/ethnicity, child age; [underlined: Funding:] CDC
Gubbels, 2011^8^; PCS, KOALA Birth Cohort Study, Netherlands; Analytic N=1513; Power Analysis: NR; [underlined: Caregiver Characteristics]; - Female: NR; - Age: Maternal age at birth: 32.2 (3.7); - SEP and/or Education: Educational level Mothers: High: 54.1%, Medium: 38.0%, Low: 7.9%; Fathers: High: 53.2%, Medium: 33.9%, Low: 12.9%; Average h worked per wk: Mothers: 18.0 (11.1) h/wk, Fathers: 37.8 (10.1) h/wk; - Race and/or Ethnicity: Country of birth: Mother: Netherlands: 97.0%, Other: 3%; Fathers: Netherlands: 96.3%, Other: 3.7%; - BMI: Maternal BMI: 24.0 (3.8), Paternal BMI: 25.0 (3.1); - Other: NA; [underlined: Child Characteristics]; - Female: 49%; - Baseline anthropometry: BMIz @ 5 y: −0.27 (0.99); Restriction: p<0.001, Stimulation healthy intake: p<0.07; - Milk feeding practices: NR; [underlined: Primary aim:] To examine parental and child associates of energy-balanced related parenting practices; to examine the association between energy balance-related parenting and activity behavior and dietary intake in 5-year-old children, and well as the prospective influence on children's BMI development up to age 7 (green arrows); to examine whether child background characteristics moderated the impact of the parenting practice. | [underlined: Exposures and Comparators:] Restriction of unhealthy intake, Monitoring, Stimulation healthy intake (Continuous); [underlined: CFP Definition]: Per CFQ; Stimulation healthy intake assessed using items "I make sure that my child eats enough healthy food products" and "I get my child enthusiastic about healthy products, such as vegetables, fruit, and whole meal products"; [underlined: CFP Assessment Method:] Child Feeding Questionnaire (CFQ)-modified.; [underlined: Child age at initial exposure measurement:] 5 y; [underlined: Outcome(s):] Growth; [underlined: Outcome assessment method]: Child's height and weight were reported by parents and used to calculated BMI. BMIz were calculated using the 1997 national reference population (i.e., the Fourth Dutch National Growth Study). Underweight @ 5 y defined as BMIz <5th percentile; [underlined: Age(s) at outcome assessment:] 7 y | Full sample (N= 1513); BMIz @ 7 y, β; [underlined: Stimulation healthy intake:] −0.06, p<0.05; Sample excluding underweight children @ 5 (N= 1326); [underlined: BMIz @ 7 y, β]; [underlined: Stimulation healthy intake]: −0.07, p<0.05 | Full sample (N=1513); BMIz @ 7 y, β; Restriction: 0.01, p>0.05; Monitoring: 0.02, p>0.05; Sample excluding underweight children @ 5 (N= 1326); BMIz @ 7 y, β; Restriction: 0.01, p>0.05; Monitoring: 0.03, p>0.05 | [underlined: Key confounders accounted for]: SEP and/or parental or caregiver education; race and/or ethnicity; child's anthropometry at baseline; child sex; parental or caregiver BMI; [underlined: Key confounders NOT accounted for:] none; [underlined: Model adjustments]: Child gender, birth weight, BMIz @ 5 y, activity style, hungry eating style, picky eating style, parental BMI, employment, educational level, country of birth, and maternal age.; [underlined: Funding]: Dutch Ministry of Economic Affairs. Dutch Ministry of Health, Welfare and Sports, FrieslandCampina, and the Dutch Sugar Bureau
Bergmeier, 2016^19^; PCS, Australia; Analytic N=72; Power Analysis: NR; [underlined: Caregiver Characteristics]; - Mothers: 100%; - Age: 36.71 (4.34 ) y; - SEP and/or Education: Annual family income: >A$105,000:39.6%, <A$25,000:4.7%; Tertiary qualification achieved: 70.7%; - Race and/or Ethnicity: Maternal country of birth: Australia: 81.5%, Europe: 7.7%, New Zealand: 3.1%, North America: 3.1%, South Africa: 3.1%, Asia: 1.5%; - BMI: Obese: 16.2%, Overweight: 41.9%, Healthy weight: 41.9%; - Other: NA; [underlined: Child Characteristics]; - Female: 56%; - Baseline anthropometry: Obese: 0%, Overweight: 21.2%, Normal weight: 75.8%, Underweight: 3.0%; NR differences bw groups; - Milk feeding practices: NR; [underlined: Primary aim:] To validate the Mutually Responsive Orientation (MRO) coding system adapted for assessing parent-child interaction during food preparation and consumption situations | [underlined: Exposures and Comparators:] Responsiveness, control (mild control, assertive control, forceful control) (Continuous); [underlined: CFP Definition:] Responsiveness in meal preparation and consumption contexts (average responsiveness scores across 3-minute segments); Control: control issues related to food issues in food preparation and food consumption contexts (overall composite score and relative frequency scores for mild, assertive and forceful control in relation to outcome measures).; [underlined: CFP Assessment Method:] Coding system developed by authors; [underlined: Child age at initial exposure measurement]: 3 y; [underlined: Outcome(s]): Growth; [underlined: Outcome assessment method:] Child weight and height were measured by trained research assistants at home visits and used to calculate BMIz according to CDC reference curves. Weight status (normal weight, overweight, or obese) was determined using sex- and age-adjusted BMIz values according to criteria from CDC; [underlined: Age(s) at outcome assessment:] 4 y | [underlined: BMIz @ 4 y, β]; Model 3:; [underlined: Responsiveness:] 0.23, p≤0.05; Model 4:; [underlined: Responsiveness:] 0.22, p≤0.05 | [underlined: BMIz @ 4 y, β]; Model 1:; Control: 0.10, p>0.05; Model 2:; [underlined: Responsiveness]: −0.03, p>0.05; Mild Control: −0.10, P>0.05 Model 3:; Assertive control: 0.12, p>0.05 Model 4:; Forceful control: 0.06, p>0.05 | [underlined: Key confounders accounted for:] SEP and/or parental or caregiver education; child's anthropometry at baseline; parental or caregiver BMI; [underlined: Key confounders NOT accounted for:] race/ethnicity; child sex; [underlined: Model adjustments]: All models: Maternal BMI, family income, approach temperament, Child BMIz at baseline Model 1: + Mutually responsive orientation, committed compliance Model 2, 3, 4: + Child responsiveness; [underlined: Funding:] Australian Research Council Discovery Grant
Quah, 2019^16^; PCS, the Growing Up in Singapore Toward; healthy Outcomes (GUSTO), Singapore; Analytic N=428; Power Analysis: NR; [underlined: Caregiver Characteristics]; - Mothers: 100%; - Age: 30.6 (5.3) y; - SEP and/or Education: None/primary/secondary: 28%, Post-secondary/tertiary: 72%; - Race and/or Ethnicity: Child Ethnicity: Chinese: 47%, Malay: 32%, Indian: 21%; - BMI: BMI @ 15 wk gestation: 24.1 (5.0); - Other: Primiparous: 44%, Multiparous: 56%; [underlined: Child Characteristics]; - Female: 49%; - Baseline anthropometry: BMIz @ 4 y: 0.22 (1.3); Overweight status (> + 2 z-score)@ 4 y: 7.8%; Normal weight: 92.2%; NR differences bw groups; - Milk feeding practices: Never BF: 3.6%, BF for <6mo: 86.4%, BF for >6 mo: 10%; [underlined: Primary aim:] To examine bidirectional associations between the 12 different maternal feeding practices (measured at 5 y) subscales and child BMI (measured at 4 and 6y) and to test the strength of bidirectional associations for feeding practices that are significantly associated with BMI. | [underlined: Exposures and Comparators:] Encouraging balance/variety, Healthy environment, Teaching about nutrition, Child involvement, Monitoring, Restriction for weight control, Restriction for health, Pressure, Emotional regulation, Child control, Food as reward (Continuous); [underlined: CFP Definition:] Per CFPQ; [underlined: CFP Assessment Method]: Comprehensive Feeding Practices Questionnaire (CFPQ); [underlined: Child age at initial exposure measurement:] 4.9 (0.2) y; [underlined: Outcome(s):]; [underlined: Outcome assessment method:] Child’s weights and heights were measured by trained staff and used to calculated BMI. Age and sex-adjusted BMI z-scores were calculated using the WHO Child Growth Standards 2007 in the WHO Anthro software.; Child overweight/obese were categorized using WHO cut-offs of above +2 z-score for children aged 4, and +1 z-score for children aged 6 years.; [underlined: Age(s) at outcome assessment]: 6 y | [underlined: BMIz @ 6 y, β (95% CI)]; Restriction for weight control: 0.02 (0.002, 0.03), p=0.024 | [underlined: BMIz @ 6 y, β (95% CI)]; Modelling: −0.02 (−0.06, 0.02), p=0.351; [underlined: Encouraging balance and variety]: −0.05 (−0.10, 0.003), p=0.048; Healthy environment: 0.02 (−0.03, 0.07), p=0.419; [underlined: Teaching about nutrition:] −0.02 (−0.08, 0.04), p=0.320; [underlined: Child involvement:] −0.05 (−0.11,−0.001), p= 0.045; Monitoring: 0.05 (0.009, 0.08), p= 0.013; Restriction for health: 0.056 (0.005, 0.11), p=0.030; Emotional regulation: 0.007 (−0.05, 0.06), p=0.811; Child control: −0.02 (−0.07, 0.02), p=0.252; Food as reward: −0.01 (−0.07, 0.05), p=0.690; Pressure: 0.01 (−0.01, 0.03), p=0.300 | [underlined: Key confounders accounted for:] SEP and/or parental or caregiver education; race and/or ethnicity; child's anthropometry at baseline; child sex; parental or caregiver BMI; [underlined: Key confounders NOT accounted for]: None; [underlined: Model adjustments:] CFPQ assessment, BMI during early pregnancy (<14 weeks), child birth order, duration of breastfeeding, ethnicity, and maternal education, BMIz at 5 y (model with restriction for weight control and pressure only); [underlined: Funding:] Singapore National Research Foundation, Translational and Clinical Research (TCR) Flagship Programme; Singapore Institute for Clinical Sciences; Agency for Science, Technology and Research (A∗STAR), Singapore; the Singapore Institute for Clinical Sciences, A∗STARand Nestec.

a Abbreviations: BMI: Body Mass Index; BMIz: Body Mass Index Z score; CFP: Caregiver feeding practice; NR: Not Reported; NA: Not Applicable; SEP: Socioeconomic position;

b Food parenting practices that fall within this bucket are underlined.

Table 17 Risk of bias for observational studies examining autonomy supportive feeding practices and growth, body composition and risk of obesity^a^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Bergmeier, 2016^19^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | LOW | HIGH | HIGH
Chong, 2017^23^ | SOME CONCERNS | HIGH | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Faith, 2013^32^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Gubbels, 2011^8^ | SOME CONCERNS | HIGH | LOW | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | HIGH
Quah, 2019^16^ | LOW | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS

a Possible ratings of low, some concerns, high, very high, no information, or not applicable were determined using the "Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)" tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602. ) *Low risk of bias except for concerns about uncontrolled confounding.

Table 18 Evidence examining the relationship between caregiver feeding styles and growth, body composition and risk of obesity ^a^,^b^

Study and Population Characteristics | Intervention/Exposure and Comparator, Outcome | Significant Results | Non-Significant Results | Confounders, Model Adjustments, Funding
Hughes, 2021^11^; PCS, U.S.; Analytic N=119; Power Analysis: Power analysis [n=187 with 95% power to detect an effect size of 0.15 for 5 predictor variables]; [underlined: Caregiver Characteristics]; - Mothers: 100%; - Age: 31.45 (6.60) y; - SEP and/or Education: Head start: 100%; Less than high school diploma: 38.3%, High school diploma or equivalent: 24.2%, Some college or more: 37.5%; Currently employed: 21.1%; - Race and/or Ethnicity: Hispanic: 100%; White: 71.9%, American Indian or Alaskan Native: 12.5%, Other (usually indicating Hispanic, Latina, or Mexican): 12.5%, Black or African American: 0.8%; - BMI: NR; - Other: Married: 59.4%, Widowed, separated, divorced: 26.5%, Never married: 14.1%; Parent immigrant status: Born in Mexico: 63.3%, Born in the U.S.: 18.0%, Born in Central America: 17.9%, Born in Cuba: 0.8%; Child born in the U.S.: 96.9%; [underlined: Child Characteristics]; - Female: 53%; - Baseline anthropometry: BMI categories at 4–5 y: Healthy (<85th percentile): 50.0%, Overweight (85th-<95th percentile): 22.7%, Obese (≥95th percentile): 27.3%; - Milk feeding practices: NR; [underlined: Primary aim:] To examine whether or not parental feeding styles at ages 4–5 continued to predict children's weight status at this later time point (7–9 y). To examine the direction of effects between parental feeding styles and child weight status. | [underlined: Exposures and Comparators:] authoritative, authoritarian, indulgent, uninvolved (Feeding style vs None); [underlined: CFS Assessment Method:] Caregiver's Feeding Styles Questionnaire (CFSQ); [underlined: Child age at initial exposure measurement:] 4–5 [Mean (SD): 4.73 (0.46)] y; [underlined: Outcome(s):] Growth; [underlined: Outcome assessment method]: Weight and height measured by trained staff. Age- and sex-specific BMI standardized scores calculated based on CDC reference standards.; [underlined: Age(s) at outcome assessment]: 7–9 y [Mean (SD): 8.31 (0.72)] | | [underlined: BMIz @ 7–9 y, β]; [underlined: Authoritarian]: −0.071, p≥0.05; [underlined: Authoritative:] 0.098, p≥0.05; [underlined: Indulgent]: 0.145, p=0.08 | [underlined: Key confounders accounted for]: SEP and/or parental or caregiver education; race and/or ethnicity; child's anthropometry at baseline; child sex; [underlined: Key confounders NOT accounted for:] Parental or caregiver BMI; [underlined: Model adjustments:] Baseline BMI z-score, child gender, child age, parental acculturation, child eating behaviors (food responsiveness, emotional overeating, satiety responsiveness), parental feeding practices (parental feeding styles only), parental feeding styles (parental feeding practices only); [underlined: Funding]: NICHD; USDA Children's Nutrition Research Center
Power, 2021^15^; PCS, None, U.S.; Analytic N=129; Power Analysis: NR; [underlined: Caregiver Characteristics]; - Mothers: ~98%, Grandmothers: ~2%; - Age: 31.5 (6.6) y; - SEP and/or Education: Education of parent: 8th grade or less: 28.7%, Some high school: 9.3%, High school diploma or GED: 24.0%, Some college or technical school: 31.0%, 4 year college graduate: 7.0%; Currently employed: 21.7%; - Race and/or Ethnicity: Latina: 100%; - BMI: Maternal BMI: Healthy (<25): 16.4%, Overweight (≥25 and <30): 30.5%, Obese (≥30): 53.1%; - Other: Marital status: Married: 59.7%, Never married: 27.2%, Widowed, separated, divorced: 13.2%; Parent immigration status: Born in U.S.: 17.7%, Born in Mexico: 63.3%, Born in Central America: 17.9%, Born in another country: 0.8%; Spanish speaking: 79.1%, English speaking: 20.9%;; [underlined: Child Characteristics]; - Female: 47%; - Baseline anthropometry: Healthy (<85th percentile): 50.4%, Overweight (85th to <95th percentile): 22.5%, Obese (≥95th percentile): 27.1%. NR differences between groups; - Milk feeding practices: NR; [underlined: Primary aim:] To examine longitudinally, over a 3.5-year period, the relationships between feeding practices, feeding styles, and young children's BMI z-scores, using both self-report and observational measures of maternal feeding. | [underlined: Exposures and Comparators:] Authoritative; Authoritarian; Indulgent; Uninvolved (Feeding style vs None); [underlined: CFS Assessment Method:] Caregiver's Feeding Styles Questionnaire; Coding based on previous literature of video recordings: Maternal demandingness was sum of frequency of all encouraging eating items (i.e., Encourage Eating, Encourage Child to Eat All the Food on the Plate, and Internal Cues References to Encourage Eating) divided by length of meal (minutes). Responsive was proportion of total strategies that were child centered. Median splits on observed demandingness and responsiveness were used to assign the 4 feeding styles; [underlined: Child age at initial exposure measurement:] 4–5 [Mean (SD): 56.8 (5.5)] mo; [underlined: Outcome(s):] Growth; [underlined: Outcome assessment method:] Height and weight measured by trained staff. Age- and sex-specific BMIz were calculated based on revised 2000 growth charts from CDC; [underlined: Age(s) at outcome assessment:] 7–9 y | [underlined: BMIz @ 7–9 y, β (SE)]; [underlined: Reason/instruct]: −3.18 (1.33), p<0.05; [underlined: CFSQ authoritative:] 0.37 (0.18), p<0.05; [underlined: CFSQ indulgent:] 0.35 (0.17), p<0.05 | [underlined: BMIz @ 7–9 y, β (SE)]; [underlined: CFSQ authoritarian]: 0.00 (0.16), p≥0.05; [underlined: Observational authoritative]: 0.19 (0.15), p≥0.05; [underlined: Observational authoritarian]: 0.22 (0.15), p≥0.05; [underlined: Observational indulgent]: −0.08 (0.15), p≥0.05; [underlined: Encourage child to eat all food on plate: −]7.19 (20.20), p≥0.05; [underlined: Encourage child to eat a different food]: −3.90 (15.44), p≥0.05; [underlined: Discourage eating:] −3.90 (15.44), p≥0.05; [underlined: Hint/acknowledge]: 1.19 (1.68), p≥0.05; [underlined: Enthusiastic modeling:] 1.27 (1.30), p≥0.05; [underlined: Question/suggestion:] 0.39 (0.95), p≥0.05; [underlined: Unelaborated command:] 0.22 (0.90), p≥0.05; [underlined: Promise food rewards:] −4.45 (2.48), p≥0.05 | [underlined: Key confounders accounted for:] Race and/or ethnicity; child's anthropometry at baseline; [underlined: Key confounders NOT accounted for:] SEP and/or parental or caregiver education; child sex; parental or caregiver BMI; [underlined: Model adjustments:] Child's baseline BMI; [underlined: Funding]: NICHD; USDA/ARS
Hughes, 2016^10^; PCS, US; Analytic N=129; Power Analysis: NR; [underlined: Caregiver Characteristics]; - Mothers: 100%; - Age: 32.01 (6.68) y; - SEP and/or Education: High school diploma or less: 62.8%, Some college or more: 37.2%, Currently employed: 24.0%; Married: 55.8%, never married: 13.2%, widowed, separated, divorced: 31%; - Race and/or Ethnicity: Latina: 100%; - BMI: NR; - Other: Parent immigrant status: born in US: 15.5%, born in Mexico: 64.3%, born in Central America: 20.2%; [underlined: Child Characteristics]; - Female: 45%; - Baseline anthropometry: Normal weight: 48.8%, Overweight: 21.7%, Obese: 29.5%, NR differences bw groups; - Milk feeding practices: NR; [underlined: Primary aim:] To investigate the influence of feeding styles and food parenting practices on low-income children's weight status over time | [underlined: Exposures and Comparators:] Authoritative, Authoritarian, Indulgent, Uninvolved (Feeding style vs None); [underlined: CFS Assessment Method:] Caregiver's Feeding Styles Questionnaire (CFSQ); [underlined: Child age at initial exposure measurement:] 4–5 y; [underlined: Outcome(s]): Growth; [underlined: Outcome assessment method:] Weight and height were measured by trained staff members. CDC reference standards were used to generate age- and gender-specific BMI z-scores.; [underlined: Age(s) at outcome assessment:] ~6 y | [underlined: BMIz @ 6 y, β]; [underlined: Indulgent vs not:] 0.114, p<0.05 | [underlined: BMIz @ 6 y, β]; [underlined: Authoritative vs not]: 0.05, p>0.05; [underlined: Authoritarian vs not]: −0.033, p>0.05; [underlined: Uninvolved vs not:] −0.02, p=0.52 | [underlined: Key confounders accounted for:] race and/or ethnicity; child's anthropometry at baseline; child sex; [underlined: Key confounders NOT accounted for:] SEP and/or parental or caregiver education; parental BMI; [underlined: Model adjustments:] Child sex, child age in months, child BMIz at baseline, acculturation (English domain), parent born in US, food responsiveness, emotional overeating, satiety responsiveness; [underlined: Funding]: NICHD, USDA-ARS
Fairley, 2015^33^; PCS, Born in Bradford birth cohort, UK; Analytic N=987; Power Analysis: NR; [underlined: Caregiver Characteristic]; - Mothers: 100%; - Age: 27.5 (5.7); - SEP and/or Education: Mother's education: ≤ GCSE equivalent: 53.7%, ≥ A-level equivalent: 38.1%; Other: 6.3%, Missing: 2.0%; - Race and/or Ethnicity: White British: 37.5%, Pakistani: 48.9%, Other: 13.4%, Missing: 2%; - BMI: Maternal BMI category @ 28 wk gestation: Underweight/normal 51.2%, Overweight: 30.1%, Obese: 18.7%; - Other: Primiparous: 37.7%, Multiparous: 59.9%, Missing: 2.4%; Smoked during pregnancy: 14.8%; [underlined: Child Characteristics]; - Female: NR; - Baseline anthropometry: NR; - Milk feeding practices: Duration of any breastfeeding: Never: 27.0%, 1 day to 1 month: 26.3%, 1 to 4 months: 18.5%, ≥ 4 months: 28.2%; Weaned <17 wk: 26.2%; [underlined: Primary aim]: To describe differences in the prevalence of potentially modifiable risk factors for childhood obesity between children of White British and Pakistani orgin and to investigate the associations between these risk factors and childhood BMI at 3 y. | [underlined: Exposures and Comparators:] Authoritative, Authoritarian, Indulgent, Uninvolved (Authoritative vs. Authoritarian vs. Indulgent vs. Uninvolved); [underlined: CFS Assessment Method:] Caregiver's feeding styles questionnaire (CFSQ); [underlined: Child age at initial exposure measurement:] 24 mo; [underlined: Outcome(s):] Growth, Weight status; [underlined: Outcome assessment method:] Weight and height were measured by researchers and used to calculated BMI and age- and sex-adjusted z-scores relative to the WHO 2006 growth standards. Overweight was defined as BMIz ≥ 85th centile; [underlined: Age(s) at outcome assessment:] 3 y | | [underlined: BMIz @ 36 mo, Mean difference (95% CI) Authoritarian vs. Authoritative (ref):] −0.10 (−0.31, 0.11), NS; [underlined: Indulgent vs. Authoritative (ref):] 0.15 (−0.06, 0.36), NS; [underlined: Uninvolved vs. Authoritative (ref]): 0.05 (−0.18, 0.28), NS; [underlined: Overweight @ 36 mo, RR (95% CI)]; [underlined: Authoritarian vs. Authoritative (ref):] 0.85 (0.60, 1.22), NS; [underlined: Indulgent vs. Authoritative (ref):] 1.29 (0.94, 1.78), NS; [underlined: Uninvolved vs. Authoritative (ref]): 1.07 (0.74, 1.55), NS | [underlined: Key confounders accounted for:] SEP and/or parental or caregiver education; race and/or ethnicity; child sex; parental or caregiver BMI; [underlined: Key confounders NOT accounted for:] Child's anthropometry at baseline; [underlined: Model adjustments:] Maternal BMI (@ 26–28 wk gestation), ethnicity, infant sex, maternal age, maternal highest educational qualification, parity, birthweight, gestational age at delivery, mode of delivery; [underlined: Funding:] NIHR
Souto-Gallardo, 2020^18^; PCS, Juega, Mexico; Analytic N=91; Power Analysis: NR; [underlined: Caregiver Characteristics]; - Mothers: 98.1%; - Age: 31.7 (7.1) y; - SEP and/or Education: Less than high school: 35.2%, High school: 18.7%, College: 46.2%; Family income per mo: ≤$265/mo: 37.8%, $265−530/mo: 37.8%, >$530/mo: 24.4%; - Race and/or Ethnicity: Mexican: 100%; - BMI: BMI: 29.1 (6.4); Normal weight: 25.3%, Overweight: 37.4%, Obesity: 37.4%; WC (Mean (25th, 75th percentile): 94.0 (82, 103); WC (% > 90th percentile): 77.5%; - Other: NA; [underlined: Child Characteristics]; - Female: 52%; - Baseline anthropometry: BMIZ at baseline (Mean, 25th, 75th percentile): 1.2 (0.4, 1.5); Baseline weight status: Underweight (≤2.0 SD): 0.0%, Normal weight: (−1.99 SD ≤ 1.0 SD) 50.0%, High risk of overweight (>1.0 SD ≤ 2.0 SD): 36.5%, Overweight (>2.0 SD ≤ 3.0 SD): 5.4%,Obesity (>3.0 SD): 8.1%; WC (% ≥90th percentile): 54.0%, Mean (25th, 75th percentile):; - Milk feeding practices: NR; [underlined: Primary aim:] To evaluate the association between food parenting practices and weight status (BMIz and waist circumference [WC]) among Mexican preschoolers and the directionality of this association after 12 months of follow-up. | [underlined: Exposures and Comparators:] Indulgent (Continuous); [underlined: CFS Assessment Method:] Toddler-Feeding Questionnaire (TFQ); [underlined: Child age at initial exposure]; [underlined: measurement:] 2–5 y (Mean (SD): (3.8 (0.6) y); [underlined: Outcome(s):] Growth, Body composition; [underlined: Outcome assessment method:] Height, weight, waist circumference measured by trained staff. Sex- and age-adjusted BMI z-scores calculated using WHO standard. Waist circumference (WC) compared with the 90th percentile of the Third National Health and Nutrition Examination Survey of Mexican American children.; [underlined: Age(s) at outcome assessment]: 3–6 y | [underlined: BMIz @ 3–6 y, β]; [underlined: Indulgent feeding]; All: 0.355, p=0.001; Boys: 0.393, p=0.008 | [underlined: BMIz @ 3–6 y, β]; [underlined: Indulgent feeding]; Girls: −0.08, p=0.71; [underlined: Change in BMIz from 2–5 y and 3–6 y, β]; [underlined: Indulgent feeding]; All: 0.020, p=0.09; Boys: 0.145, p=0.35; Girls: 0.029, p=0.08; [underlined: Change in WC from 2–5 y and 3–6 y, β]; [underlined: Indulgent feeding]; All: 0.067, p=0.53; Boys: 0.111, p=0.47; Girls: −0.106, p=0.54 | [underlined: Key confounders accounted for]: Race and/or ethnicity; child sex; [underlined: Key confounders NOT accounted for:] SEP and/or parental or caregiver education; child's anthropometry at baseline; parental or caregiver BMI; [underlined: Model adjustments:] Other feeding practices; [underlined: Funding:] NR
Papaioannou, 2023^14^; PCS, US; Analytic N=129; Power Analysis: NR; [underlined: Caregiver Characteristics]; - Mothers: 100%; - Age: 31.55 (6.60) y; - SEP and/or Education: > High school: 38%, High school or equivalent: 24%, Some college or more: 38%; Employed: 20.9%; Attending Headstart: 100%; - Race and/or Ethnicity: Hispanic: 100%; - BMI: NR; - Other: Parent: Married: 58.9%, Never married: 14%, widowed/separated/divorced: 27.1%; Parent born in US: 17.8%, Born in Mexico: 63.5%, Born in Central America: 17.9%; Child: Born in U.S: 96.9%; [underlined: Child Characteristics]; - Female: 54%; - Baseline anthropometry: Underweight (<5th percentile): 1.6, Healthy weight (5th to <85th percentile): 48.8% Overweight (85th to <95th percentile): 22.5% Obese (≥95th percentile): 27.1%; Pressure to eat: p<0.001, Authoritarian: p<0.05, Indulgent: p<0.05; - Milk feeding practices: NR; [underlined: Primary aim:] To examine the degree to which individual differences in children’s food motivation in the preschool years interacted with mothers’ feeding styles in predicting subsequent weight status in Hispanic children from low−income levels. | [underlined: Exposures and Comparators]: Authoritative, Authoritarian, Indulgent, Uninvolved (Authoritative vs Uninvolved, Authoritarian vs Uninvolved, Indulgent vs Uninvolved); [underlined: CFS Assessment Method:] Caregiver’s Feeding Styles Questionnaire (CFSQ); [underlined: Child age at initial exposure measurement:] 4–5 y (Mean (SD): 4.76 (0.46) y); [underlined: Outcome(s):] Growth; [underlined: Outcome assessment method:] Height and weight were measured by trained staff. Age- and gender-specific BMI z-scores were calculated using the CDC Reference Standards.; [underlined: Age(s) at outcome assessment:] 8.34 (0.71) y | [underlined: BMIz @ ~ 8 y, β (95% CI)]; [underlined: Authoritative vs. Uninvolved (ref]): 0.39 (0.03, 0.75), p<0.05; [underlined: Indulgent vs. Uninvolved (ref):] 0.40 (0.06, 0.73), p<0.05 | [underlined: BMIz @ ~ 8 y, β (95% CI)]; [underlined: Authoritarian vs. Uninvolved (ref):] −0.10 (−0.43, 0.22), p≥0.05 | [underlined: Key confounders accounted for]: Race and/or ethnicity, SEP and/or parental or caregiver education, child's anthropometry at baseline; [underlined: Key confounders NOT accounted for:] Parental or caregiver BMI; [underlined: Model adjustments:] Child BMIZ @ time 1, CFQ feeding practices, CFSQ feeding styles, highly motivated eating score, 3 feeding styles by highly motivated eating interactions; [underlined: Funding:] NICHD, USDA/ARS
Perez, 2021^35^; PCS, US; Analytic N=219; Power Analysis: NR; [underlined: Caregiver Characteristics]; - Mothers: 100 %; - Age: 27.79 (6.48) y; - SEP and/or Education: Maternal education: 10.14 (3.21); Estimated total income: <$5,000: 13.7%, $5,001-$10,000: 18.9%, $10,001-$15,000: 27.0%, $15,001−$20,000:11.5%, $20,001-$25,000: 13.4%, ≥$25,001: 13.9%; - Race and/or Ethnicity: Mexican/ Mexican-American: 100%; - BMI: NR; - Other: Mothers' origin of birth: US: 14%, Mexico: 86%; Marital Status: Married: 30%, Living with a partner: 45%, Never married: 15%; Number of other biological children: 1.98 (1.68); [underlined: Child Characteristics]; - Female: 54%; - Baseline anthropometry: WLZ% @ 2 y: 67.91 (28.50); NR differences bw groups; - Milk feeding practices: NR; [underlined: Primary aim:] To examine if child weight-for-length trajectories from 6 wk to 2 y were associated with maternal demandingness and responsiveness at 3 y, and if maternal feeding dimensions predicted child BMI trajectories from 4.5 to 7.5 y among Mexican American children from low-income families. | [underlined: Exposures and Comparators:] Demandingness, Responsiveness (Continuous); [underlined: CFS Assessment Method:] Caregiver Feeding Styles Questionnaire (CFSQ); [underlined: Child age at initial exposure measurement:] 3 y; [underlined: Outcome(s):] Growth, Weight status; [underlined: Outcome assessment method:] Child's length/height and weight were assessed by trained staff and used to calculate weight-for-length percentile z-scores (WLZ%) using the WHO software. BMI percentile z-scores (BMIz%) were calculated at 4.5, 6 and 7.5 y using the WHO software. Overweight was defined as BMI >85th up to 95th percentile.; Age(s) at outcome assessment: 4.5–7.5 y | [underlined: BMIz% (intercept) @4.5 y, β (SE)]; [underlined: Demandingness]: −0.172 (0.073), p=0.018; [underlined: Overweight classification 4.5–7.5 y]; [underlined: Low demandingness (1 SD above mean):] BMIz @ 61st percentile; [underlined: High demandingness (1 SD below mean):] BMIz @ 70th percentile | [underlined: BMIz% (intercept) @4.5 y, β (SE)]; [underlined: Responsiveness]: NS; [underlined: BMIz% (slope) 4.5–7.5 y, β (SE)]; [underlined: Demandingness]: NS; [underlined: Responsiveness * Demandingness (interaction):] NS | Key confounders accounted for: race/Ethnicity; child's anthropometry at baseline; [underlined: Key confounders NOT accounted for:] SEP and/or parental or caregiver education; child sex; parental or caregiver BMI; [underlined: Model adjustments:] Maternal acculturation, infant temperamental regulation, WLZ% @ 2 y (overweight), child effortful control and self-regulation @ 4.5 y; [underlined: Funding:] NICHD, NIMHD
Worobey, 2014^36^; PCS, US; Analytic N=80; Power Analysis: NR; [underlined: Caregiver Characteristics]; - Mothers: 100%; - Age: 31 (5) y; - SEP and/or Education: WIC:100%, Mean level of education: 1 y high school (SD 3.5 y) Race and/or Ethnicity: African American: 11%, Latina: 23%, Mexican immigrants: 66%; - BMI: NR; - Other: NA; [underlined: Child Characteristics]; - Female: 38%; - Baseline anthropometry: BMI% @ 3 y: 72.17 (25.21); NS differences bw groups; - Milk feeding practices: NR; [underlined: Primary aim:] To explore whether parent feeding styles were associated with BMI in a cohort of low-income preschool-age children and if the authoritative feeding style would be predictive of a lower weight status. | [underlined: Exposures and Comparators:] Authoritative, Authoritarian, Indulgent, Uninvolved (Authoritative vs. Authoritarian vs. Indulgent vs. Uninvolved); [underlined: CFS Assessment Method:] Caregiver Feeding Styles Questionnaire (CFSQ); [underlined: Child age at initial exposure measurement]: 3 y [Mean (SD): 3.04 y (57 d)]; [underlined: Outcome(s):] Growth; [underlined: Outcome assessment method:] Height and weight were measured by trained research assistants and used to calculate BMI. BMI percentiles were calculated (reference data not reported); [underlined: Age(s) at outcome assessment:] 4 y (3.99 y (31 d)) | [underlined: Change in BMI% 3–4 y, Mean (SD), t Value Authoritarian:] 67.44 (24.7)−81.80 (20.9), −2.30, p<0.03 | [underlined: Change in BMI% 3–4 y, Mean (SD), t Value Authoritative:] 70.36 (25.6)−70.40 (23.9), −0.10, p<0.99; [underlined: Indulgent:] 78.75 (25.5)-82.48 (21.8), −0.47, p<0.64; [underlined: Uninvolved:] 71.71 (25.3)−72.76 (25.9), −0.14, p<0.89 | [underlined: Key confounders accounted for:] None; [underlined: Key confounders NOT accounted for:] SEP and/or parental or caregiver education; race and/or ethnicity; child's anthropometry at baseline; child sex; parental or caregiver BMI; [underlined: Model adjustments:] None; [underlined: Funding:] NICHD and NJAES
Kamdar, 2019^34^; PCS, U.S.; Analytic N=126; Power Analysis: NR; [underlined: Caregiver Characteristics]; - Mothers: 98.4%, Grandmothers: 1.6%; - Age: NR; - SEP and/or Education: Some high school or less: 38.7%, High school/GED: 24.1%, Technical school/ Some college: 32.1%, College graduate: 5.1%; - Employed: 23.4%, Unemployed: 76.6% Race and/or Ethnicity: Hispanic: 100%; - BMI: Maternal BMI: 31.90 (7.20); - Other: Maternal Hispanic acculturation: 3.64 (0.51), Maternal English acculturation: 2.20 (0.88) High/marginal food security: 54.0%, Low food security: 28.5%, Very low food security: 17.5% HeadStart families: 100%; Child Characteristics; - Female: 48%; - Baseline anthropometry: Underweight (< 5th Percentile): 0.7%, Normal (5th < 85th Percentile): 48.9%, Overweight (85th < 95th Percentile): 21.2%, Obese: 29.2%; - Milk feeding practices: NR; [underlined: Primary aim:] To investigate if food insecurity affects child body mass index (BMI) through parental feeding demandingness and/or responsiveness and dietary quality 18 months later among low-income Hispanic preschooler | [underlined: Exposures and Comparators:] Other (Demandingness (1–5): 3.07, Responsiveness (.20–2.02): 1.22); [underlined: CFS Assessment Method:] Caregiver Feeding Style Questionnaire (CFSQ); [underlined: Child age at initial exposure measurement:] 4.8 y; [underlined: Outcome(s):] Growth; [underlined: Outcome assessment method:] Height and weight were measured by trained staff. Age and gender specific BMI z-scores were calculated based on the CDC Reference Standards; [underlined: Age(s) at outcome assessment]: 6.3 y | | BMIz@ ~ 6y, B (SE); [underlined: Demandingness:] −0.14 (0.07), NS; BMIz@ ~ 6y, B (SE); [underlined: Responsiveness:] −0.16 (0.27), NS | [underlined: Key confounders accounted for:] SEP and/or parental or caregiver education; race and/or ethnicity; child's anthropometry at baseline; child sex; parental or caregiver BMI; [underlined: Key confounders NOT accounted for:] None; [underlined: Model adjustments:] Child gender, number of household members and children, parental Hispanic and English acculturation, marital status, parental employment status, parental education level, parental BMI, child BMI at baseline. Cross lagged model also included food insecurity; [underlined: Funding:] National Institute of Child Health and Human Development; the Robert Wood Johnson Future of Nursing Scholars Program.

a Abbreviations: BMI: Body Mass Index; BMIz: Body Mass Index Z score; CFS: Caregiver feeding style; CFSQ: Caregiver Feeding Styles Questionnaire; NR: Not Reported; NA: Not Applicable; SEP: Socioeconomic position

b Feeding styles that fall within this bucket are underlined.

Table 19 Risk of bias for observational studies examining caregiver feeding styles and growth, body composition and risk of obesity^a^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Fairley, 2015^33^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Hughes, 2016^10^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Hughes, 2021^11^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Papaioannou, 2023^14^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Perez, 2021^35^ | HIGH | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Power, 2021^15^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Souto-Gallardo, 2020^18^ | HIGH | SOME CONCERNS | LOW | LOW | LOW | LOW | LOW | HIGH
Worobey, 2014^36^ | VERY HIGH | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | VERY HIGH
Kamdar, 2019^34^ | LOW | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS

a Possible ratings of low, some concerns, high, very high, no information, or not applicable were determined using the "Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)" tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602. ) *Low risk of bias except for concerns about uncontrolled confounding.