# Results

## Literature search and screening results

The literature search (Appendix 3) yielded 32283 search results after the removal of duplicates (see Figure 2). Dual-screening resulted in the exclusion of 26215 titles, 5045 abstracts, and 989 full-texts articles. Reasons for full-text exclusion are in Appendix 4. Two additional articles were identified from the manual search. The body of evidence included 36 articles.

Figure 2 Literature search and screen flowchart

The literature search in PubMed, Embase, Cochrane, and CINAHL, retrieved 32,283 records after removing duplicates. 2 were found with manual search methods. 26,215 titles, 5,045 abstracts, and 989 full-texts were excluded. 36 articles were included in the systematic review.

## Structured feeding practices

### Description of the evidence

A total of 18 articles (15 independent studies) met inclusion criteria that examined the associations between caregiver feeding practices related to structuring child’s physical and social environment and growth, body composition and risk of obesity.^1–18^ All articles were prospective cohort studies (PCS).

Fifteen of the 18 included articles examined associations of caregiver feeding practices involving monitoring of children’s eating with growth, body composition and risk of obesity (Table 10).^1,3–5,7,8,10–18^ The body of evidence also included 7 articles that examined associations of family meals,^6,9^ covert control,^1,17^ food availability,^2^ healthy environment,^16^ and/or modeling^7,16^ with outcomes related to growth, body composition and risk of obesity (Table 12). Due to the number of studies examining caregiver feeding practices involving monitoring of children’s eating, the 2025 Dietary Guidelines Advisory Committee reviewed and synthesized the evidence separately.

#### Population

##### Monitoring

The 15 articles from PCS were from 12 independent cohorts; 4 articles were from the same longitudinal cohort study.^10,11,14,15^ Sample sizes ranged from N=57^5^ to N=4166^12^ participants with 4 articles reporting sample sizes of greater than 500 participants.^1,4,8,12^ Five articles reported information from a power analysis and were adequately powered to detect differences in desired outcomes.^4,10,11,14,15^ One study reported being underpowered.^5^

The studies took place in the U.S.,^5,10,11,13–15^ Australia,^3,7,17^ Netherlands,^8,12^ Germany,^4^ Mexico,^18^ Portugal,^1^ and Singapore.^16^

Caregivers were mostly mothers with a mean age between 30 and 35 years.^1,3,4,7,17^ Five of the 15 articles did not report information about participants’ racial and/or ethnic background^1,3,4,7,17^ and 1 article did not report information on participants’ socioeconomic position.^5^. Of those that did report on race and/or ethnicity, 6 articles reported 100% participants were Mexican, Hispanic or Latino,^10,11,13–15,18^ 1 article reported 100% participants were white,^5^ 1 article reported that participants were predominantly Dutch,^16^ and 1 article reported 47% participants from Chinese, 32% from Malay and 21% from Indian origin.^3,4,7,8,12,16,17^ Seven articles reported that >50% of participants were with middle to higher SEP^1,10,11,13–15,18^ and 7 articles reported that >50% of participants were with low SEP.^1,10,11,13–15,18^

Regarding children in the studies, girls and boys were fairly evenly represented with samples ranging from 45%^10^ to 58%^3^ female. The percentage of children with overweight or obesity at baseline was reported as follows: ≥ 50% in 4 articles,^10,11,14,15^ 48% in 1 article,^9^ 15% in 1 article^7^ and 13% in 2 articles.^3,18^

##### Other structures feeding practices

The 7 studies that included evidence on other structured feeding practices took place in the U.S.,^2,6,9^ Australia,^7,17^ Portugal,^1^ and Singapore.^16^ Sample sizes ranged from N=106^7^ to N=8000^6^ with 3 articles reporting sample sizes of greater than 2000 participants.^1,6,16^ Power analyses were not reported in any of the articles.

Caregiver type was reported in 6 of the 7 articles; 4 articles included 100% mothers,^1,7,16,17^ 1 article included 100% fathers,^9^ and 1 article included 67% mothers/stepmothers, 9% father/stepfathers, 16% grandmothers, and 18% other.^2^ The mean caregiver age ranged from approximately 30 to 35 years. Three of the 7 articles did not report information about participant’s race and/or ethnicity^1,7,16,17^ and 1 article did not report information on SEP.^2,7^ Of those that did report on race and/or ethnicity, 2 articles reported that participants were predominantly white,^6,9^ 1 article reported 100% American Indian participants living on a reservation^2^ and 1 article reported 47% participants from Chinese, 32% from Malay and 21% from Indian origin.^16^ Five articles reported participants from higher SEP^6,7,9,16,17^ and 1 article reported participants from lower SEP.^1^

Regarding children in the studies, girls and boys were fairly evenly represented with samples ranging from 48%^9^ to 52%^6^ female. Articles with information on children’s weight status at baseline reported the percentage of children with overweight or obesity as follows: 48% in 1 article,^9^ 29% in 1 article,^2^ 15% in 1 article,^7^ and 8% in 1 article.^16^

#### Exposure/Comparator

Structure involves caregivers’ organization of children’s environment to facilitate children’s competence.^*^ Structured feeding practices encompass caregivers’ consistent enforcement of rules and boundaries about eating, strategies used by caregivers to help their children learn and maintain certain dietary behaviors, and the caregivers’ physical organization of their children’s food environment. These practices may include rules, limits or boundaries, limited/guided choices, portion size, monitoring, meal- and snack time routines (atmosphere of meals, distractions [e.g., screens], family presence, and meal and snack schedule), modeling, food availability and accessibility, and food preparation, and unstructured (indulgent) feeding practices.

* Vaughn AE, Ward DS, Fisher JO, . Fundamental constructs in food parenting practices: a content map to guide future research. Nutr Rev. 2016 Feb;74(2):98–117.26724487

##### Monitoring

In 14 of the 15 studies, caregiver’s monitoring of children’s eating was measured at a single timepoint when children were on average 2 years,^17^ 3 years,^3,7^ 4 years,^1,10–15,18^ or 5 years of age.^5,8,16^ Two studies assessed monitoring at multiple timepoints.^4,13^ All studies assessed caregiver’s monitoring of children’s intake of less healthy foods (e.g. sweets and high fat foods) using self-reported questionnaires.^1,3–5,7,8,10–18^

##### Other structured feeding practices

Other structured feeding practices were measured at a single timepoint when children were on average 2 years,^9,17^ 3 years,^7^ 4 years,^1^ or 5 years of age.^2,16^ One study assessed caregiver feeding practices at multiple time-points when children were on average between 5 and 8 years.^6^ All studies assessed caregiver feeding practices using self-reported questionnaires. There was wide variability in the feeding practices that were assessed across studies: 2 studies assessed frequency of family meals,^6,9^ 2 studies assessed covert control,^1,17^ 1 study assessed food availability of 47 food and beverage items at home,^2^ 1 study assessed both modeling and healthy environment,^16^ and 1 study assessed modeling of healthy eating.^7^

#### Outcome

##### Monitoring

All 15 articles examined outcomes related to growth; 13 articles examined children’s BMI z-scores at a single, follow-up timepoint^1,3–5,7,8,10–12,14–16,18^ and 3 articles examined changes in children's BMI z-scores,^17,18^ or BMI percentiles^13^ between 2 timepoints. One article also assessed waist circumference as a measure of body composition.^18^ In most studies, anthropometric measures used to calculate outcomes were obtained by trained staff using standard protocols; 3 articles used measures reported by parents.^3,7,8^

Outcomes were assessed anywhere from 3 months^13^ to 3.5 years^11,14,15^ after baseline with a majority of articles (10 articles) assessing outcomes between 1 and 2 years after baseline.^3–5,7,8,10,12,16–18^

##### Other structured feeding practices

Four studies examined outcomes related to growth; 3 studies examined children’s BMI z-scores at a single, follow-up timepoint^1,7,16^ and 1 study examined changes in children's BMI z-scores between 2 timepoints.^17^

Three studies assessed overweight status or risk of overweight or obesity at follow-up using cutoffs according to Center for Disease Control and Prevention (CDC) growth references.^2,6,9^ Six studies used anthropometric measurements obtained by trained staff or researchers to calculate growth, body composition and risk of obesity (GBCO) outcomes^1,2,6,9,16,17^ and 1 study used measurements reported by mothers.^7^ The follow-up duration for outcome assessment ranged from 1 year^7,16,17^ to 3 years.^1^

### Synthesis of the evidence

#### Monitoring

Nine of the 15 articles that examined monitoring of children’s eating and growth, body composition and risk of obesity reported null associations.^1,3,7,8,12,13,16–18^ Of the 6 articles that reported statistically significant findings with outcomes related to growth, 5 articles reported negative associations with BMI z-scores at follow-up^5,10,11,14,15^; 1 study reported negative association with BMI z-scores at follow-up for children with low risk for overweight/obesity but not for children with high risk for overweight/obesity,^5^ and 4 articles that reported on data from the same longitudinal cohort reported negative associations between monitoring with BMI z-scores.^10,11,14,15^ One study reported a positive association between monitoring assessed when children were 5 years old with BMI z-scores at 1 year follow-up, but no effect when children were 2, 3, 4, or 6 years old.^4^

#### Other structured feeding practices

Studies in this body of evidence assessed a range of feeding practices related to structuring child’s physical and social environment and growth, body composition and risk of obesity and reported mostly null findings. Among the studies that reported statistically significant results, there was heterogeneity in the direction and magnitude of the effect. Guerrero et al.^9^ reported that greater frequency of breakfasts with fathers, but not frequency of dinners with fathers, was associated with a higher odds of having overweight at follow-up.^9^ In another study, children who had fewer family meals per week had a lower odds ratio of having overweight at follow-up or for maintaining overweight at follow-up.^6^ The only other study to assess outcomes related to risk of obesity reported that changes in the levels of home food availability of snacks and unhealthful foods was not associated with changes in the probability of having normal weight, overweight, or obesity at follow-up.^2^

Two studies assessed modeling with outcomes related to growth and showed no effect.^7,16^ There was also no association between healthy environment and children’s BMI z-scores at follow-up.^16^ Studies that assessed covert control reported negative associations with BMI z-scores at follow-up, but these associations did not reach significance.^1,17^

Studies had numerous risk of bias concerns across domains (Table 11, Table 13). The primary risk of bias concerns were related to not accounting for key confounders, self-reported exposures and outcomes, post-exposure interventions that could influence the relationship between exposures and outcomes, and lack of pre-registered analysis plans. Publication bias was also a consideration; however this was not assessed as a serious concern because the body of evidence predominantly included studies that reported only nonsignificant findings, as well as studies that reported a mix of both significant and nonsignificant results, across a range of analytic sample sizes. However, while the literature search was comprehensive, a search of the gray literature was not done, which could increase the possibility of publication bias.

### Conclusion statements and grades

#### Monitoring

The 2025 Dietary Guidelines Advisory Committee developed conclusion statements to answer the question, “What is the relationship between parental and caregiver feeding styles and practices during childhood and growth, body composition and risk of obesity?” based on their review of the body of evidence on monitoring by caregivers of children ages 2 to 6 years (Table 5).

Table 5 Conclusion statement, grades for structured feeding practices (monitoring) and growth, body composition, and risk of obesity

Conclusion Statement | Food parenting practices involving monitoring of children's eating by caregivers of children ages 2 to 6 years is not associated with outcomes related to growth. This conclusion statement is based on evidence graded as limited.
Grade | Limited
Body of Evidence | 15 articles: 15 PCS
Consistency | Few concerns with consistency across the body of evidence.
Precision | Substantial concerns with precision due to small sample sizes of cohorts and lack of randomized controlled trials.
Risk of bias | Substantial concerns with risk of bias due to confounding, missing data, and exposure and outcome measurement.
Directness | Few concerns with directness across the body of evidence.
Generalizability | Substantial concerns with generalizability to the US population due to limited race and/or ethnic diversity and caregivers primarily being mothers across the body of evidence.

##### Assessment of the evidence

The body of evidence underlying the graded conclusion statement above includes 15 articles from 12 independent PCS. The evidence was graded based on an assessment of 5 grading elements, as described below.

###### Consistency

The direction of the findings was somewhat consistent in that structured food parenting practices involving monitoring of children’s eating was not associated with growth.

###### Precision

There were concerns with precision due to small sample sizes in the cohorts and lack of randomized controlled trials.

###### Risk of bias

Risk of bias assessments for each article are detailed in Table 11. There were serious concerns with numerous risks of bias domains, which may potentially influence the results that were reported in the articles. There were concerns with confounding since many articles from observational studies did not account for key confounders. Across the body of evidence, the measurement of caregiver feeding practices was a potential concern due to the use of self-report and non-validated assessment measures. Outcome measurement was also a concern for articles that used parent reported height and weight measurements. Many articles had issues with missing data and did not provide evidence that their results were not biased. Lastly, the selection of reported results was a concern for articles that did not pre-register data analysis plans.

###### Directness

Most articles directly examined the relationship between caregiver monitoring of children’s eating and growth, body composition and risk of obesity.

###### Generalizability

There were some concerns with generalizing the findings to the U.S. populations. Three of the 12 the studies (6 of 15 articles) were from the U.S., and the majority of participants in these studies were Hispanic or Latino and white. Only a few articles included participants from diverse racial and ethnic backgrounds. Additionally, few studies reported on feeding practices from caregivers other than children’s mothers.

#### Other structured feeding practices

The Committee did not draw a conclusion statement about the relationship between other caregiver feeding practices related to structuring children’s physical and social environment, specifically, availability of healthy foods, modeling of healthy eating behaviors, meal routines such as eating together as a family and growth, body composition and risk of obesity because there was not enough evidence available (Table 6).

Table 6 Conclusion statement, grades for structured feeding practices (other structured feeding practices) and growth, body composition, and risk of obesity

Conclusion Statement | A conclusion statement cannot be drawn about the relationship between food parenting practices by caregivers of children ages 2 to 6 years that structure children’s physical and social eating environments (e.g., availability of healthy foods, modeling of healthy eating behaviors, meal routines such as eating together as a family) and outcomes related to growth, body composition, and risk of obesity because there was not enough evidence available.
Grade | Grade Not Assignable
Body of Evidence | 7 articles: 7 PCS
Rationale | There was a small number of studies available to answer this question and there were inconsistencies in the structured feeding practices and GBCO outcomes that were assessed making it difficult to synthesize the evidence.

## Controlling feeding practices

### Description of the evidence

Twenty-eight articles met inclusion criteria and examined associations between controlling feeding practices and growth, body composition and risk of obesity among children 2 to 6 years.^1,3–5,7,8,10–31^ All 28 articles were from PCS (Table 14).

#### Population

The 28 articles from PCS were from 24 independent studies; 4 articles reported data from the same longitudinal cohort study^10,11,14,15^ and 2 articles reported data from the same sample of mothers.^17,31^ Sample sizes ranged from N=39^25^ to N=7312^23^ participants with 9 studies reporting sample sizes of greater than 500 participants.^1,4,8,12,23,24,27,28,30^ Five articles reported information from a power analysis and were adequately powered to detect differences in desired outcomes.^4,10,11,14,15^ Two articles reported being underpowered.^5,29^

The studies took place in the U.S.,^5,10,11,13–15,21,26,30^ Australia/ New Zealand,^3,7,17,19,20,22,29,31^ Netherlands,^8,12,24,28^ U.K.,^23,25^ Portugal,^1^ Germany,^4^ Mexico,^18^ France,^27^ and Singapore.^16^

In 18 articles, caregivers were 100% mothers ^1,3,7,10–12,14,16,17,19,20,23–25,27,29–31^ and in 6 articles, caregivers were predominantly (≥80%) mothers.^5,13,15,18,21,28^ The remaining articles reported caregivers to be a mix of mothers, grandmothers, fathers or other,^26^ 50% females^22^ and 100% parents.^4^ One article did not report caregiver type.^8^ Ten of the 28 articles did not report information about participant’s race and/or ethnicity^3,4,7,17,19,20,22,27,29,31^ and 2 articles did not report information on SEP.^5,26^ Of those that did report on race and/or ethnicity, 5 studies were from predominantly white populations,^5,21,23,25,30^ 8 articles reported that >50% of participants were from underrepresented racial and/or ethnic groups^10,11,13–16,18,26^ and 4 articles reported that children were predominantly Dutch.^8,12,24,28^ Educational attainment was the most common type of SEP information reported though some articles only provided information on participants’ household income. Nineteen studies were conducted among samples with middle to higher SEP^3,4,7,8,12,16,17,19–25,27–31^ and 7 studies were conducted in lower SEP samples.^1,10,11,13–15,18^

Regarding children in the samples, girls and boys were fairly evenly represented ranging from 45%^10^ to 58%^3^ female. Four articles reported that ≥ 50% of children in the sample were with overweight or obesity at baseline.^10,11,14,15^

#### Exposure/Comparator

In 25 of the 28 articles, caregiver feeding practices were measured at a single timepoint when children were on average 2 years,^17,27,31^ 3 years,^3,7,19,20,23,29^ 4 years,^1,10,11,14,15,18,21,24,28,30^ or 5 years old.^5,8,16,26^ Three studies assessed caregiver feeding practices at multiple timepoints.^4,12,22^ The most frequently assessed controlling feeding practice was restriction^1,3–5,7,8,10–18,20–22,24,25,27,29,31^, followed by pressure to eat^1,3–5,7,10–12,14–17,20,27,29^ and instrumental feeding.^4,16–18,27,28^ Four articles assessed emotional feeding^16,17,23,27^ and 5 studies assessed general controlling feeding practices.^1,17,19,26,30^ Most articles assessed caregiver feeding practices using self-reported questionnaires, however 5 articles reported using observational methods, such as coding of video-recorded meals.^15,19–21,25^

#### Outcome

All 28 studies examined outcomes related to growth; 22 studies measured children’s BMI z-scores at a single, follow-up timepoint^1,3–5,7,8,10–12,14–16,18–20,22–28^ and 6 studies measured changes in children's BMI z-scores or BMI percentiles between 2 timepoints.^13,17,21,29–31^ Four studies examined measures of body composition: 3 studies measured fat mass or percent body fat,^21,23,26^ 3 studies measured waist circumference,^18,21,26^ and 2 studies measured skinfold thickness.^21,26^ Three studies assessed overweight status or risk of overweight using cutoffs according to growth references.^21,26,28^

Follow-up duration ranged from 3 months^13^ to approximately 11 years.^23^ A majority of articles (11 articles) reported a follow-up duration of 1 year. ^3,7,16–20,26,29,31^ Three articles assessed outcomes at multiple time points occurring 2, 4, and 6 years after baseline,^27^ 3 and 5 years after baseline^30^ and 3.5 and 11.5 years after baseline.^23^

### Synthesis of the evidence

Across the 28 studies, associations between controlling feeding practices and GBCO outcomes varied in direction and magnitude of the effect. In 7 of the 28 studies, controlling feeding practices by caregivers of children 2 to 6 years were associated with greater BMI z-scores at follow-up or greater change in BMI z-score from baseline to follow-up^10,16–18,25,27,29^ and in 6 of the 28 studies, controlling feeding practices were associated with lower BMI z-scores or BMI at follow-up.^1,3,12,20,28,30^ One study reported both positive and negative associations between controlling feeding practices with BMI z-scores.^5^ A majority of studies also reported 1 or more null association between a controlling feeding practice with a GBCO outcome.

There was considerable variation in the direction of the association and magnitude of effect between specific controlling feeding practices with GBCO outcomes. Of the 21 studies that assessed restriction, 6 studies reported positive associations with BMI z-scores,^5,10,16,18,25,27^ 2 studies reported negative associations with BMI z-scores,^19,22^ and 14 studies reported no association between restriction and children’s BMI z-score,^1,3,4,7,8,11,13–15,17,21,24,29,31^ change in waist circumference,^18^ risk of overweight,^21^ or BMI.^12^ Similar variability was reported between pressure to eat and GBCO outcomes with 1 study reporting positive associations with BMI z-scores,^29^ 3 studies reporting negative associations with BMI z-score or BMI,^1,5,12^ and 12 studies reporting no association between pressure to eat with BMI z-score^3,4,7,10,11,14–18,20,27^ or change in waist circumference.^18^ Five studies found no association between emotional feeding with BMI z-scores, fat mass, or changes in waist circumference.^16–18,23,27^ Six studies reported associations between instrumental feeding with GBCO outcomes: Rodgers et al.^17^ reported positive associations between instrumental feeding with BMI z-score change, Eichler et al.^4^ and Quah et al.^16^ reported using food as reward was not associated with BMI z-scores at follow up, and Jansen et al^28^ reported that using food as reward was not associated with BMI z-scores or risk of overweight or obesity. Two studies reported positive associations for certain subgroups: Guivarch et al.^27^ reported positive associations between high use of food as reward and BMI z-scores among boys only and Souto-Gallardo et al.^18^ reported positive associations between food reward and change in BMI z-scores among girls only. Findings between GBCO outcomes with other forms of controlling feeding practices were similarly mixed.^1,17,19,26,30^ A full summary of the included studies is presented in (Table 14).

The lack of association between controlling feeding practices and GBCO outcomes in this body of evidence may be due to methodological limitations, as noted by high or very high risk of bias across the studies. Specifically, many studies had issues with confounding and missing data. Almost all the observational studies assessed exposures using caregiver self-report at a single timepoint. Further, there was considerable heterogeneity in outcome assessment, including duration of follow-up and number of assessments. There were concerns with precision as no trials were included in the body of evidence and concerns with generalizability as studies did not reflect the diversity of the U.S. population. Risk of bias assessments are outlined in Table 15.

Publication bias was also a consideration; however this was not assessed as a serious concern because the body of evidence included studies that reported a mix of both significant and nonsignificant results, as well as studies that reported only nonsignificant findings across a range of analytic sample sizes. However, while the literature search was comprehensive, a search of the gray literature was not done, which could increase the possibility of publication bias.

### Conclusion statement and grade

The 2025 Dietary Guidelines Advisory Committee developed a conclusion statement to answer the question, “What is the relationship between parental and caregiver feeding styles and practices during childhood and growth, body composition and risk of obesity?” based on their review of the body of evidence on controlling feeding practices by caregivers of children ages 2 to 6 years (Table 7). A conclusion statement could not be drawn due to substantial concerns with consistency and directness in the body of evidence.

Table 7 Conclusion statement, grades for controlling feeding practices and growth, body composition, and risk of obesity

Conclusion Statement | A conclusion statement cannot be drawn about the relationship between controlling feeding practices by caregivers of children ages 2 to 6 years and outcomes related to growth, body composition, and risk of obesity because there are substantial concerns with consistency in the body of evidence.
Grade | Grade Not Assignable
Body of Evidence | 28 articles: 28 PCS
Rationale | The available evidence was too inconsistent to draw meaningful conclusions on the relationship between controlling feeding practices and growth, body composition and risk of obesity. There was considerable variability in the direction and magnitude of effect.

## Autonomy supportive feeding practices

### Description of the evidence

Five articles met inclusion criteria and assessed associations between food parenting practices that provide developmentally appropriate support for children’s autonomy and GBCO outcomes (Table 16).^8,16,19,23,32^ All articles were from PCS.

#### Population

The PCS were conducted in the U.S.^32^, UK,^23^ Netherlands,^8^ Australia,^19^ and Singapore,^16^ and included data from participants enrolled in the following cohorts: the Avon Longitudinal Study of Parents and Children (ALSPAC), the National Longitudinal Study of Youth (NLSY), The KOALA Birth Cohort Study, and the Growing up in Singapore Toward Healthy Outcomes (GUSTO). The analytic sample size ranged from N=72 participants^19^ to N=7312 participants.^23^ Power analyses were not reported in any of the articles.

Four of the 5 studies included 100% mothers; the fifth study included data from both mothers and fathers.^8^ The caregivers had a mean age of approximately 25 to 35 years with 1 study conducted in Australia reporting that caregivers were on average 37 years.^19^ Maternal BMI was reported in 4 studies and ranged from approximately 23 to 24, indicating that mothers were in the “healthy” weight category.^8,16,23,32^ The fifth article reported that over 50% of mothers were with overweight or obesity.^19^

Information on participants’ race and/or ethnicity was provided in 2 articles: 1 article reported 3.9% of participants were non-white ethnicity^23^ and 1 article reported approximately 39% of participants were Non-Hispanic/non-African American, approximately 34% were African American, and approximately 27% were Hispanic.^32^ The other articles included information on heritage of participants and/or country of birth e.g., “Netherlands”,^8^ “Australia”^19^ or “Chinese, Malay or Indian”.^16^

Four of 5 articles provided information on participants’ SEP, mostly in the form of highest level of education achieved: 2 articles reported >70% of participants had post-secondary/tertiary qualification,^16,19^ 1 article reported >90% of mothers achieved medium or high education level,^8^ and 1 article reported >50% of participants achieved O Level, A Level or Degree status.^23^

In terms of the children in this body of evidence, boys and girls were fairly evenly represented with most studies reporting samples that were approximately 49% female^8,16,23,32^ and 1 study reporting a sample that was 56% female.^19^ Four of 5 articles reported that a majority of children were “healthy weight” at baseline, indicated by a BMI percentile <85 and/or a BMI z-score < 2.^8,16,19,32^

#### Exposure/Comparator

Studies measured caregiver feeding practices when children were approximately 3,^19,23^ 4,^32^ or 5 years.^8^ Four studies used self-reported questionnaires^8,16,23,32^ and 1 study used observational measures to assess food parenting practices that provide developmentally appropriate support for children’s autonomy.^19^

Reported feeding practices varied across studies: 2 studies assessed parent versus child food choice,^23,32^ 1 study assessed simulation of healthy eating^8^ and 1 study assessed a variety of practices including encouraging balance/variety, teaching about nutrition, and child involvement when children were on average 5 years of age.^16^ In Bergmeier et al.^19^ video-recorded mealtime observations were coded to assess maternal responsiveness when children were approximately 3 years of age.

#### Outcome

Outcomes were measured when children were approximately 4 through 7 years with 2 studies conducting additional, longer-term follow-ups when children were >10 years.^23,32^ All 5 studies examined outcomes related to growth with the most commonly reported outcome being BMI z-score. Additionally, 1 study examined outcomes related to body composition (e.g., body fat)^23^ and 1 study reported on risk of obesity (e.g., BMI).^32^ Anthropometric measurements were obtained by trained researchers or staff members in 4 of 5 studies.^16,19,23,32^ The fifth study used measures reported by parents.^8^

### Synthesis of the evidence

The direction and magnitude of effects of feeding practices that provide developmentally appropriate support for children’s autonomy on growth, body composition and risk of obesity varied widely within and across studies. In 1 study, higher parental versus child food choice at 3.5 years was not associated with BMI z-score at 7 years but did predict lower BMI z-scores and fat mass at 15 years.^23^ In another study, parent versus child food choice did not predict child BMI z-score or incidence of overweight or obesity at follow-up.^32^ One study reported that stimulation of healthy intake at 5 years was negatively associated with BMI z-score at 7 years.^8^ The fourth study examined multiple feeding practices that provide developmentally appropriate support for children’s autonomy and reported that encouraging balance and variety, child involvement, and teaching about nutrition at 5 years did not predict child BMI z-scores at 6 years.^16^

The only study to report observed measures of feeding practices examined the associations between observed maternal responsiveness at 3 years and BMI z-score at 4 years. After controlling for varying degrees of maternal control, this study reported that observed maternal responsiveness was positively associated with child BMI z-score when controlling for assertive or forceful control, but not when controlling for mild control.^19^

Studies had numerous risk of bias concerns across domains (Table 17). The primary risk of bias concerns were related to not accounting for key confounders, self-reported exposures and outcomes, post-exposure interventions that could influence the relationship between exposures and outcomes, and lack of a pre-registered analysis plan. Publication bias was also a consideration; however this was not assessed as a serious concern because the body of evidence predominantly included studies that reported only nonsignificant findings, as well as studies that reported a mix of both significant and nonsignificant results, across a range of analytic sample sizes. However, while the literature search was comprehensive, a search of the gray literature was not done, which could increase the possibility of publication bias.

### Conclusion statement and grade

The 2025 Dietary Guidelines Advisory Committee developed a conclusion statement to answer the question, “What is the relationship between parental and caregiver feeding styles and practices during childhood and growth, body composition and risk of obesity?” based on their review of the body of evidence on feeding practices by caregivers of children ages 2 to 6 years that provide developmentally appropriate support for children’s autonomy (Table 8). A conclusion statement could not be drawn due to substantial concerns with consistency in the body of evidence.

Table 8 Conclusion statement, grades for autonomy supportive feeding practices and growth, body composition, and risk of obesity

Conclusion Statement | A conclusion statement cannot be drawn about the relationship between food parenting practices by caregivers of children ages 2 to 6 years that provide developmentally appropriate support for children's autonomy (e.g., responsive feeding, praise, child involvement in food and eating activities) and outcomes related to growth, body composition, and risk of obesity because there are few studies and substantial concerns with consistency in the body of evidence.
Grade | Grade Not Assignable
Body of Evidence | 5 articles: 5 PCS
Rationale | Only 5 studies met inclusion criteria and assessed autonomy supportive feeding practices and growth, body composition and risk of obesity. The available evidence had considerable variability in the measured exposures and the direction and magnitude of results.

## Feeding styles

### Description of the evidence

Nine articles met inclusion criteria and examined associations between caregiver feeding styles and growth, body composition and risk of obesity among children age 2 to 6 years.^10,11,14,15,18,33–36^ All 9 articles were from PCS (Table 18).

#### Population

The 9 articles were from 6 independent studies: 4 articles reported on data from the same cohort.^10,11,14,15^ The studies took place in the U.S.,^10,11,14,15,34–36^ U.K.,^33^ and Mexico.^18^ Sample sizes ranged from N=80 participants^36^ to N=987 participants^33^ with a majority of studies reporting sample sizes of <200 participants.^10,11,14,15,18,34,36^ Four articles reported information from a power analysis and were adequately powered to detect differences in desired outcomes.^10,11,14,15^

Caregivers were characterized as 98%^15,18,34^ or 100% mothers.^10,11,14,33,35,36^ Information on race and/or ethnicity and SEP were provided in all 9 articles. Seven articles reported that 100% of participants were categorized as Mexican or Hispanic,^10,11,14,15,18,34,35^ 1 study included participants that were categorized as 66% Mexican immigrants, 23% Latina and 11% African American,^36^ and 1 study included approximately 50% Pakistani and 37% White British.^33^ In terms of SEP, 6 articles enrolled families participating in income-based assistance programs (e.g., Head Start, WIC)^10,11,14,15,34,36^ and all articles reported that a majority of participants achieved high school or less education.^10,11,14,15,18,33–36^ Maternal BMI was reported in 4 articles.^15,18,33,34^ In these studies, the mean BMI was >25 or >50% of participants had a BMI ≥25, indicating that a majority of mothers were with overweight or obesity.

In terms of children in the studies, 7 articles reported that approximately 50% of the sample were female,^10,11,14,15,18,34,35^ 1 article reported 38% female^36^, and 1 article did not report sex or gender of the participants.^33^ Six of the 9 articles reported that approximately 50% of children were characterized as having overweight or obesity at baseline, defined as BMI >85^th^ percentile^10,11,14,15,34^ or high risk of overweight, defined as BMI z-score >1.0.^18^ Two articles reported the mean BMI percentile or weight-for-length z-score percentile was approximately 68^35^ and 72.^36^

#### Exposure/Comparator

Feeding styles were assessed when children were on average 2 years, ^33^3 years,^35,36^ 4 years^10,11,14,15,18^ or 5 years of age.^34^ All 9 studies used self-reported questionnaires to assess caregiver feeding styles.^10,11,14,15,18,33–36^ Seven of 9 studies categorized caregivers to a single feeding style according to their levels of demandingness and responsiveness^10,11,14,15,18,33,36^; caregivers were categorized as Authoritarian, Authoritative, Indulgent or Uninvolved. Two studies assessed caregivers varying degrees of demandingness and responsiveness as continuous variables.^34,35^

#### Outcome

All 9 studies examined outcomes related to growth with the most commonly reported outcome being BMI z-score.^10,11,14,15,18,33,34^ One study also examined outcomes related to body composition (e.g., change in waist circumference)^18^ and 2 studies also examined outcomes related to risk of obesity (e.g., overweight classification).^33,35^ Anthropometric measures used to calculate outcomes were obtained by trained staffusing standard protocols.

Children’s ages when outcomes were assessed varied widely between studies. Children were on average 3 years,^33^ 4 years,^36^ 6 years,^10,34^ or 8 years^11,14,15^ or ranged from 3 to 6 years.^18^ One study assessed outcomes at multiple timepoints when children were on average 4.5 years and 7.5 years.^35^

### Synthesis of the evidence

Seven articles examined associations between categorical feeding styles with GBCO outcomes^10,11,14,15,18,33,36^ and of these, 4 reported on data from the same cohort of participants.^10,11,14,15^ These 4 articles reported that an indulgent feeding style was associated with increased child BMI z-scores compared with other feeding styles.^10,11,14,15^ Additionally, Power et al.^15^ and Papaioannou et al.^14^ reported an authoritative feeding style was positively associated with children’s BMI z-scores at the 3.5 year follow-up. One other study reported positive associations between caregiver’s indulgent feeding style with children’s BMI z-scores, but further stratification by gender showed this association was stronger for boys than for girls.^18^ This same study did not find any effects of indulgent feeding style on change in children’s BMI z-score or waist circumference from baseline to follow-up. Worobey and Trytko ^36^ reported that an authoritarian feeding style was associated with a significant change in children’s BMI percentile from 3 to 4 years. The seventh article reported null associations between feeding styles with BMI z-scores.^33^

Perez et al.^35^ and Kamdar et al.^34^ both assessed associations of caregiver’s demandingness and responsiveness (as continuous scores) with children’s GBCO outcomes. Perez et al.^35^ reported that demandingness was associated with lower BMI z-score percentiles at baseline, but not change in BMI z-score percentiles from baseline to follow-up. Low demandingness did predict a lower BMI z-score percentile at follow-up compared with high demandingness. Responsiveness was not associated with children’s GBCO outcomes. Kamdar et al.^34^ reported no associations between demandingness or responsiveness with children’s BMI z-scores at follow-up.

The differences in findings across studies in this body of evidence may be due to methodological limitations, as noted by concerns related to bias in all of the studies (Table 19). Main areas of concerns were issues with confounding, measurement of exposures using self-report, missing data, and lack of pre-registered analysis plans. There was also heterogeneity in the exposures, comparators, and outcomes across studies, with studies using different reference groups and measures of feeding styles, as well as different follow-up durations. Further, studies were not entirely generalizable since they did not reflect the diversity of the U.S. population. This body of evidence included both large and small studies with significant as well as null findings, so publication bias may have been less likely. However, while the literature search was comprehensive, a search of the gray literature was not done, which could increase the possibility of publication bias.

### Conclusion statement and grade

The 2025 Dietary Guidelines Advisory Committee developed a conclusion statement to answer the question, “What is the relationship between parental and caregiver feeding styles and practices during childhood and growth, body composition and risk of obesity?” based on their review of the body of evidence on feeding styles by caregivers of children ages 2 to 6 years (Table 9). A conclusion statement could not be drawn due to substantial concerns with consistency in the body of evidence.

Table 9 Conclusion statement, grades for feeding styles and growth, body composition and risk of obesity

Conclusion Statement | A conclusion statement cannot be drawn about the relationship between feeding styles by caregivers of children ages 2 to 6 years and outcomes related to growth, body composition, and risk of obesity because there are substantial concerns with consistency in the body of evidence.
Grade | Grade Not Assignable
Body of Evidence | 9 articles: 9 PCS
Rationale | The evidence available to answer this question had high variability in the comparators, assessment timing, and inconsistencies in the direction and magnitude of effect between exposures and outcomes making it difficult to synthesize together.