# Introduction

To prepare for the development of the Dietary Guidelines for Americans, 2025–2030, the U.S. Departments of Health and Human Services (HHS) (Appendix 1) and Agriculture (USDA) identified a proposed list of scientific questions based on relevance, importance, potential federal impact, and avoiding duplication, which were posted for public comment.^*^ The Departments appointed the 2025 Dietary Guidelines Advisory Committee (Committee) in January 2023 to review evidence on the scientific questions. The Committee’s review of the evidence forms the basis of the Scientific Report of the 2025 Dietary Guidelines Advisory Committee ^†^, which includes independent, science-based advice and recommendations to HHS and USDA and is considered during the development of the next edition of the Dietary Guidelines.

* Dietary Guidelines for Americans: Learn About the Process. 2022. Available at: https://www.dietaryguidelines.gov/work-under-way/learn-about-process

† 2025 Dietary Guidelines Advisory Committee. 2024. Scientific Report of the 2025 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Health and Human Services and Secretary of Agriculture. U.S. Department of Health and Human Services. 10.52570/DGAC2025

The proposed scientific questions were refined and prioritized by the Committee for consideration in their review of the evidence. As part of that process, the following systematic review question was prioritized: What is the relationship between parental and caregiver feeding styles and practices during childhood and growth, body composition, and risk of obesity? The Committee conducted a systematic review to address this question, with support from USDA’s Nutrition Evidence Systematic Review (NESR) team. This review is a new review that complements and expands upon an existing systematic review on parental and caregiver feeding practices from birth to 24 months and growth, body composition and risk of obesity that was conducted by the Pregnancy and Birth to 24 Months Project Flavor Exposure and Feeding Practices Technical Expert Collaborative (Table 1), and the conclusion statements developed as part of that existing work can be found in Appendix 2.

Table 1 Review history

Date | Description | Citation
April 2019 | Systematic review conducted by the Pregnancy and Birth to 24 Months Project, Flavor Exposure and Feeding Practices Technical Expert Collaborative published, focused on infants and young children, birth to 24 months | Spill M, Callahan E, Johns K, Shapiro M, Spahn JM, Wong YP, Terry N, Benjamin-Neelon S, Birch L, Black M, Briefel R, Cook J, Faith M, Mennella J, Casavale KO, Stoody E. Parental and Caregiver Feeding Practices and Growth, Size, and Body Composition Outcomes: A Systematic Review. April 2019. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: 10.52570/NESR.PB242018.SR0402.
May 2023 | Systematic review protocol for the 2025 Dietary Guidelines Advisory Committee published online | Fisher JO, Abrams SA, Andres A, Byrd-Bredbenner C, Deierlein A, Eicher-Miller HA, Odoms-Young A, Palacios C, Obbagy J, Kim JH, Lawless M, Momin S, Spahn J, Higgins M, Butera G, Terry N. Parental and Caregiver Feeding Styles and Practices and Growth, Body Composition and Risk of Obesity: A Systematic Review Protocol. May 2023. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: https://nesr.usda.gov/protocols
February 2024 | Revisions to the systematic review protocol for the 2025 Dietary Guidelines Advisory Committee published online | Fisher JO, Abrams SA, Andres A, Byrd-Bredbenner C, Deierlein A, Eicher-Miller HA, Odoms-Young A, Palacios C, Obbagy J, Kim JH, Lawless M, Momin S, Spahn J, Higgins M, Butera G, Terry N. Parental and Caregiver Feeding Styles and Practices and Growth, Body Composition and Risk of Obesity: A Systematic Review Protocol. May 2023. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: https://nesr.usda.gov/protocols
June 2024 | Revisions to the systematic review protocol for the 2025 Dietary Guidelines Advisory Committee published online | Fisher JO, Abrams SA, Andres A, Byrd-Bredbenner C, Deierlein A, Eicher-Miller HA, Odoms-Young A, Palacios C, Obbagy J, Kim JH, Lawless M, Momin S, Spahn J, Higgins M, Butera G, Terry N. Parental and Caregiver Feeding Styles and Practices and Growth, Body Composition and Risk of Obesity: A Systematic Review Protocol. May 2023. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: https://nesr.usda.gov/protocols