# Plain language summary

### What is the question?

The question is: What is the relationship between parental and caregiver feeding styles and practices during childhood and growth, body composition and risk of obesity? The population of interest for this question includes children ages 2 to 6 years.

### Why was this question asked?

This systematic review was conducted by the 2025 Dietary Guidelines Advisory Committee as part of the process to develop the Dietary Guidelines for Americans, 2025–2030.

### How was this question answered?

The Committee conducted a new systematic review to answer this question with support from the USDA Nutrition Evidence Systematic Review team.

### What is the answer to the question?

- Food parenting practices involving monitoring of children's eating by caregivers of children ages 2 to 6 years is not associated with outcomes related to growth. This conclusion statement is based on evidence graded as limited.
- A conclusion statement cannot be drawn about the relationship between food parenting practices by caregivers of children ages 2 to 6 years that structure children’s physical and social eating environments (e.g., availability of healthy foods, modeling of healthy eating behaviors, meal routines such as eating together as a family) and outcomes related to growth, body composition, and risk of obesity because there was not enough evidence available.
- A conclusion statement cannot be drawn about the relationship between controlling feeding practices by caregivers of children ages 2 to 6 years and outcomes related to growth, body composition, and risk of obesity because there are substantial concerns with consistency in the body of evidence.
- A conclusion statement cannot be drawn about the relationship between food parenting practices by caregivers of children ages 2 to 6 years that provide developmentally appropriate support for children's autonomy (e.g., responsive feeding, praise, child involvement in food and eating activities) and outcomes related to growth, body composition, and risk of obesity because there are few studies and substantial concerns with consistency in the body of evidence.
- A conclusion statement cannot be drawn about the relationship between feeding styles by caregivers of children ages 2 to 6 years and outcomes related to growth, body composition, and risk of obesity because there are substantial concerns with consistency in the body of evidence.

### How up-to-date is this systematic review?

Conclusion statements from this review are based on articles published between January 2000 and July 2023.