# Appendix 4 Excluded articles

The following table lists the articles excluded after full-text screening for this systematic review question. At least 1 reason for exclusion is provided for each article, though this may not reflect all possible reasons. Information about articles excluded after title and abstract screening is available upon request.

Table A 7 Articles excluded after full-text screening

| Citation | Rationale
1 | National Association of Pediatric Nurse Practitioners. Healthy Eating and Activity Together (HEAT) Clinical Practice Guideline: Identifying and Preventing Overweight in Childhood. Journal of Pediatric Healthcare. 2006;20:S1–63. | Study design
2 | Ohri-Vachaspati P, Berry A. Environmental, Parental, and Demographic Determinants of Home Food Environment. Journal of Nutrition Education & Behavior. 2012;44(4 Supplement):S61–S61. | Study design
3 | Chan, MS. The Association of Parental Feeding and Child Eating Behavior with Young Children BMI in Preschool Settings in Hong Kong. Journal of Nutrition Education & Behavior. 2012;44(4 Supplement):S48–S49. | Publication status
4 | Aboud FE, Shafique S, Akhter S. A responsive feeding intervention increases children's self-feeding and maternal responsiveness but not weight gain. J Nutr. Sep 2009;139(9):1738–43. doi:10.3945/jn.109.104885.19587124 | Country
5 | Adab P, Pallan MJ, Cade J, Preventing childhood obesity, phase II feasibility study focusing on South Asians: BEACHeS. BMJ Open. Apr 10 2014;4(4):e004579. doi:10.1136/bmjopen-2013-004579. | Intervention/exposure
6 | Adams EL, Caccavale LJ, Smith DI, Bean MK. Food Insecurity, Federal Nutrition Support, and Parent Feeding Practices During COVID-19: A 1-Year Follow-up Study. Public Health Rep. Mar-Apr 2023;138(2):323–332. doi:10.1177/00333549221132532.36416035 | Outcome
7 | Adams EL, Marini ME, Brick TR, Paul IM, Birch LL, Savage JS. Ecological momentary assessment of using food to soothe during infancy in the INSIGHT trial. International Journal of Behavioral Nutrition & Physical Activity. 2019;16(1):N.PAG–N.PAG. | Outcome
8 | Adkins S, Sherwood NE, Story M, Davis M. Physical activity among African-American girls: the role of parents and the home environment. Obes Res. Sep 2004;12 Suppl:38s–45s. doi:10.1038/oby.2004.267.15489466 | Study design
9 | Afonso L, Castro J, Parente N, Torres S. A Comprehensive Assessment of Food Parenting Practices: Psychometric Properties of the Portuguese Version of the HomeSTEAD Family Food Practices Survey and Associations with Children's Weight and Food Intake. Eur J Investig Health Psychol Educ. Feb 5 2020;10(1):424–440. doi:10.3390/ejihpe10010032. | Study design
10 | Agras WS, Hammer LD, Huffman LC, Mascola A, Bryson SW, Danaher C. Improving healthy eating in families with a toddler at risk for overweight: a cluster randomized controlled trial. J Dev Behav Pediatr. Sep 2012;33(7):529–34. doi:10.1097/DBP.0b013e3182618e1f.22947882 | Outcome
11 | Agras WS, Hammer LD, McNicholas F, Kraemer HC. Risk factors for childhood overweight: a prospective study from birth to 9.5 years. J Pediatr. Jul 2004;145(1):20–5. doi:10.1016/j.jpeds.2004.03.023.15238901 | Intervention/exposure
12 | Aguayo L, Olave-Pichon A, Ariza AJ, Binns HJ. Characteristics of Very Young Hispanic Children Referred for Obesity Management. Glob Pediatr Health. 2017;4:2333794x17739192. doi:10.1177/2333794x17739192. | Study design; Intervention/exposure; Outcome
13 | Ahn JS, Min S, Kim MH. The Role of Uncontrolled Eating and Screen Time in the Link of Attention Deficit Hyperactivity Disorder with Weight in Late Childhood. Psychiatry Investig. Nov 2017;14(6):808–816. doi:10.4306/pi.2017.14.6.808. | Study design
14 | Al-Dalaeen AM, Al-Domi HA. Factors Associated with Obesity among School Children in Amman, Jordan. Malaysian Journal of Nutrition. 2017;23(2):211–218. | Intervention/exposure
15 | Alghadir AH, Gabr SA, Iqbal ZA. Television watching, diet and body mass index of school children in Saudi Arabia. Pediatr Int. Apr 2016;58(4):290–4. doi:10.1111/ped.12834.26383788 | Study design; Intervention/exposure
16 | Al-Ghamdi SH. The association between watching television and obesity in children of school-age in Saudi Arabia. J Family Community Med. May 2013;20(2):83–9. doi:10.4103/2230-8229.114767.23983559 | Study design; Intervention/exposure
17 | Allen HA, Chambers A, Blissett J, Relationship between Parental Feeding Practices and Neural Responses to Food Cues in Adolescents. PLoS One. 2016;11(8):e0157037. doi:10.1371/journal.pone.0157037.27479051 | Study design; Intervention/exposure; Outcome
18 | Almaamary S, Al Shammakhi S, Alghamari I, Jabbour J, Al-Jawaldeh A. Preschoolers' and Mothers Dietary Practices and Compliance with the 24-h Movement Guidelines: Results of Oman's National Nutrition Survey. Int J Environ Res Public Health. Aug 23 2021;18(16). doi:10.3390/ijerph18168867. | Study design; Outcome
19 | Alqaoud N, Al-Jawaldeh A, Al-Anazi F, Subhakaran M, Doggui R. Trend and Causes of Overweight and Obesity among Pre-School Children in Kuwait. Children (Basel). Jun 19 2021;8(6). doi:10.3390/children8060524. | Study design
20 | Al-Qaoud NM, Al-Shami E, Prakash P. Kuwaiti mothers' perception of their preschool children's weight status. J Dev Behav Pediatr. Jul-Aug 2010;31(6):505–10. doi:10.1097/DBP.0b013e3181e56dc7.20611037 | Study design; Intervention/exposure
21 | Al-Qerem WA, Ling J, AlBawab AQ. Validation of the comprehensive feeding practice questionnaire among school aged children in Jordan: a factor analysis study. Int J Behav Nutr Phys Act. Feb 20 2017;14(1):23. doi:10.1186/s12966-017-0478-y.28219402 | Study design; Age of all participants at intervention/exposure
22 | Altman M, Cahill Holland J, Lundeen D, Reduction in food away from home is associated with improved child relative weight and body composition outcomes and this relation is mediated by changes in diet quality. J Acad Nutr Diet. 2015;115(9):1400–1407. doi:10.1016/j.jand.2015.03.009 25963602 | Intervention/exposure
23 | Alvarado BE, Zunzunegui MV, Delisle H, Osorno J. Growth trajectories are influenced by breastfeeding and infant health in an afro-colombian community. J Nutr. Sep 2005;135(9):2171–8. doi:10.1093/jn/135.9.2171.16140894 | Intervention/exposure
24 | Amianto F, Martini M, Olandese F, Affectionless control: A parenting style associated with obesity and binge eating disorder in adulthood. Eur Eat Disord Rev. Mar 2021;29(2):178–192. doi:10.1002/erv.2809.33247868 | Study design; Age of some participants at I/E
25 | Amuta AO, Jacobs W, Idoko EE, Barry AE, McKyer EL. Influence of the Home Food Environment on Children's Fruit and Vegetable Consumption: A Study of Rural Low-Income Families. Health Promot Pract. Sep 2015;16(5):689–98. doi:10.1177/1524839915589733.26055463 | Study design
26 | Anand SS, Davis AD, Ahmed R, A family-based intervention to promote healthy lifestyles in an aboriginal community in Canada. Can J Public Health. Nov-Dec 2007;98(6):447–52. doi:10.1007/bf03405436.19039880 | Intervention/exposure
27 | Andaya AA, Arrendondo EM, Alcaraz JE, Lindsay SP, Elder JP. The Association between Family Meals, TV Viewing during Meals, and Fruit, Vegetables, Soda, and Chips Intake among Latino Children. Journal of Nutrition Education & Behavior. 2011;43(5):308–315. doi:10.1016/j.jneb.2009.11.005.20965787 | Study design
28 | Andersen LB, Mølgaard C, Michaelsen KF, Carlsen EM, Bro R, Pipper CB. Indicators of dietary patterns in Danish infants at 9 months of age. Food Nutr Res. 2015;59:27665. doi:10.3402/fnr.v59.27665.26111966 | Intervention/exposure; Outcome
29 | Anderson CB, Hughes SO, Fisher JO, Nicklas TA. Cross-cultural equivalence of feeding beliefs and practices: the psychometric properties of the child feeding questionnaire among Blacks and Hispanics. Prev Med. Aug 2005;41(2):521–31. doi:10.1016/j.ypmed.2005.01.003.15917048 | Study design; Outcome
30 | Anderson JD, Newby R, Kehm R, Barland P, Hearst MO. Taking steps together: a family- and community-based obesity intervention for urban, multiethnic children. Health Educ Behav. Apr 2015;42(2):194–201. doi:10.1177/1090198114547813.25150275 | Intervention/exposure
31 | Anderson LM, Symoniak ED, Epstein LH. A randomized pilot trial of an integrated school-worksite weight control program. Health Psychol. Nov 2014;33(11):1421–5. doi:10.1037/hea0000007.23895201 | Intervention/exposure; Age at outcome
32 | Andrews KR, Silk KS, Eneli IU. Parents as health promoters: a theory of planned behavior perspective on the prevention of childhood obesity. J Health Commun. Jan 2010;15(1):95–107. doi:10.1080/10810730903460567.20390979 | Study design
33 | Annus AM, Smith GT, Fischer S, Hendricks M, Williams SF. Associations among family-of-origin food-related experiences, expectancies, and disordered eating. Int J Eat Disord. Mar 2007;40(2):179–86. doi:10.1002/eat.20346.17089412 | Intervention/exposure; Outcome
34 | Antal H, Buckloh L, Lochrie A, Milkes A, Wysocki T. Family-based intervention for overweight youth: effects on health-related quality of life and measurements of physical health. Journal article; Conference proceeding. Diabetes. 2010. | Publication status
35 | Antoniou EE, Roefs A, Kremers SP, Picky eating and child weight status development: a longitudinal study. J Hum Nutr Diet. 2016;29(3):298–307. doi:10.1111/jhn.12322 25988483 | Intervention/exposure
36 | Anwar A, Anwar F, Joiya HU, Prevalence of obesity among the school-going children of Lahore and associated factors. J Ayub Med Coll Abbottabad. Oct-Dec 2010;22(4):27–32.22455255 | Study design; Country
37 | Anzman SL, Birch LL. Low inhibitory control and restrictive feeding practices predict weight outcomes. J Pediatr. Nov 2009;155(5):651–6. doi:10.1016/j.jpeds.2009.04.052.19595373 | Intervention/exposure
38 | Anzman-Frasca S, Liu S, Gates KM, Paul IM, Rovine MJ, Birch LL. Infants' Transitions out of a Fussing/Crying State Are Modifiable and Are Related to Weight Status. Infancy. 2013;18(5):662–686. doi:10.1111/infa.12002.25302052 | Intervention/exposure
39 | Ardakani A, Monroe-Lord L, Wakefield D, Castor C. Parenting Styles, Food Parenting Practices, Family Meals, and Weight Status of African American Families. Int J Environ Res Public Health. Jan 12 2023;20(2) doi:10.3390/ijerph20021382. | Study design
40 | Arluk SL, Branch JD, Swain DP, Dowling EA. Childhood obesity's relationship to time spent in sedentary behavior. Mil Med. Jul 2003;168(7):583–6.12901472 | Intervention/exposure
41 | Arredondo EM, Elder JP, Ayala GX, Campbell N, Baquero B, Duerksen S. Is parenting style related to children's healthy eating and physical activity in Latino families? Health Educ Res. Dec 2006;21(6):862–71. doi:10.1093/her/cyl110.17032706 | Study design
42 | Augustine JM, Prickett KC, Kimbro R. Health-Related Parenting among U.S. Families and Young Children's Physical Health. J Marriage Fam. Jun 2017;79(3):816–832.. doi: 10.1111/jomf.12363.28959075 | Intervention/exposure
43 | Avery A, Pallister C, Allan J, Stubbs J, Lavin J. An initial evaluation of a family-based approach to weight management in adolescents attending a community weight management group. J Hum Nutr Diet. 2012;25(5):469–476. doi:10.1111/j.1365-277X.2012.01277.x 22834988 | Study design; Intervention/exposure; Outcome
44 | Ayala GX, Rogers M, Arredondo EM, Away-from-home food intake and risk for obesity: examining the influence of context. Obesity (Silver Spring). May 2008;16(5):1002–8. doi:10.1038/oby.2008.34.18309297 | Study design; Intervention/exposure
45 | Ayatollahi SM, Sharafi Z, Haem E. Child Weight Growth Chart and Its Associated Factors in Birth Cohort of Maku Using a Growth Curve Model and LMS Method. Glob J Health Sci. Apr 19 2015;7(6):181–6. doi:10.5539/gjhs.v7n6p181.26153171 | Intervention/exposure
46 | Ayine P, Selvaraju V, Venkatapoorna CMK, Geetha T. Parental Feeding Practices in Relation to Maternal Education and Childhood Obesity. Nutrients. Apr 9 2020;12(4) doi:10.3390/nu12041033. | Age of all participants at intervention/exposure
47 | Backman DR, Haddad EH, Lee JW, Johnston PK, Hodgkin GE. Psychosocial predictors of healthful dietary behavior in adolescents. J Nutr Educ Behav. Jul-Aug 2002;34(4): 184–92. doi: 10.1016/s1499-4046(06)60092-4.12217261 | Intervention/exposure; Outcome
48 | Balantekin KN, Savage JS, Marini ME, Birch LL. Parental encouragement of dieting promotes daughters' early dieting. Appetite. Sep 2014;80:190–6. doi:10.1016/j.appet.2014.05.016.24858835 | Intervention/exposure
49 | Banchonhattakit P, Tanasugarn C, Pradipasen M, Miner KR, Nityasuddhi D. Effectiveness of school network for childhood obesity prevention (SNOCOP) in primary schools of Saraburi Province, Thailand. Southeast Asian J Trop Med Public Health. 2009;40(4):816–834.19842420 | Intervention/exposure
50 | Barbosa C, Lopes C, Costa A, Warkentin S, Oliveira A. Parental child-feeding practices at 4 years of age are associated with dietary patterns of 7-year-olds. J Hum Nutr Diet. Feb 16 2023. doi:10.1111/jhn.13151. | Outcome
51 | Barnes SP, Brown KM, McDermott RJ, Bryant CA, Kromrey J. Perceived Parenting Style and the Eating Practices of College Freshmen. American Journal of Health Education. 2012;43(1):8 17. | Study design; Age of some participants at I/E
52 | Barr-Anderson DJ, van den Berg P, Neumark-Sztainer D, Story M. Characteristics associated with older adolescents who have a television in their bedrooms. Pediatrics. Apr 2008;121(4):718–24. doi:10.1542/peds.2007-1546.18381536 | Study design
53 | Baskind MJ, Taveras EM, Gerber MW, Fiechtner L, Horan C, Sharifi M. Parent-Perceived Stress and Its Association With Children's Weight and Obesity-Related Behaviors. Prev Chronic Dis. Mar 28 2019;16:E39. doi:10.5888/pcd16.180368.30925139 | Study design
54 | Bauer KW, Larson Nl, Nelson MC, Story M, Neumark-Sztainer D. Socio-environmental, personal and behavioural predictors of fast-food intake among adolescents. Public Health Nutr. Oct 2009; 12(10):1767–74.19105866 | Outcome
55 | Bauer KW, Laska MN, Fulkerson JA, Neumark-Sztainer D. Longitudinal and secular trends in parental encouragement for healthy eating, physical activity, and dieting throughout the adolescent years. J Adolesc Health. Sep 2011;49(3):306–11. doi:10.1017/s1368980008004394.21856524 | Outcome
56 | Bauer KW, Lumeng JC, Sonneville KR. Parenting in an Obesogenic Environment: Ghosts at the Dinner Table. Pediatrics. 2018;141(4):1–2. doi:10.1016/j.jadohealth.2010.12.023. | Publication status
57 | Bauer KW, Neumark-Sztainer D, Fulkerson JA, Story M. Adolescent girls' weight-related family environments, Minnesota. Prev Chronic Dis. May 2011;8(3):A68.21477508 | Study design; Outcome
58 | Baughcum AE, Powers SW, Johnson SB, Maternal feeding practices and beliefs and their relationships to overweight in early childhood. J Dev Behav Pediatr. Dec 2001;22(6):391–408. doi:10.1097/00004703-200112000-00007.11773804 | Study design
59 | Baur L. Effectiveness of a home-based early intervention on children's BMI at age two years: randomised controlled trial. Journal article; Conference proceeding. Obesity facts. 2012;5:34-. | Intervention/exposure
60 | Baxter KA, Ware RS, Batch JA, Truby H. Predicting success: factors associated with weight change in obese youth undertaking a weight management program. Journal article. Obesity research & clinical practice. 2013;7(2):e147–e154. doi:10.1016/j.orcp.2011.09.004.24331776 | Intervention/exposure; Comparator
61 | Bean MK, Wilson DB, Thornton LM, Kelly N, Mazzeo SE. Dietary intake in a randomizedcontrolled pilot of NOURISH: a parent intervention for overweight children. Prev Med. Sep 2012;55(3):224–7. doi:10.1016/j.ypmed.2012.06.016.22735041 | Intervention/exposure; Outcome
62 | Belardinelli P, Torbica A, Fattore G. Longitudinal associations between different measures of socioeconomic status and health behavior among adolescents. Data from a wealthy Italian region. Article. Preventive Medicine. 2022;160. doi:10.1016/j.ypmed.2022.107092. | Intervention/exposure
63 | Bellisle F, Rolland-Cachera MF. Three consecutive (1993, 1995, 1997) surveys of food intake, nutritional attitudes and knowledge, and lifestyle in 1000 French children, aged 9–11 years. J Hum Nutr Diet. Jun 2007;20(3):241–51. doi:10.1111/j.1365-277X.2007.00773.x.17539877 | Study design; Intervention/exposure
64 | BeLue R, Francis LA, Rollins B, Colaco B. One size does not fit all: identifying risk profiles for overweight in adolescent population subsets. J Adolesc Health. Nov 2009;45(5):517–24. doi:10.1016/j.jadohealth.2009.03.010.19837359 | Study design
65 | Bennett AE, Johnston Molloy C, Glennon-Slattery C, Loane D. Outcomes of a CommunityBased Paediatric Weight Management Programme in an Irish Midlands Setting. Ir Med J. Feb 9 2018; 111 (2):689.29952438 | Intervention/exposure
66 | Berge JM, Wall M, Hsueh TF, Fulkerson JA, Larson N, Neumark-Sztainer D. The protective role of family meals for youth obesity: 10-year longitudinal associations. J Pediatr. 2015;166(2):296 301. doi: 10.1016/j.jpeds.2014.08.030 25266343 | Age of all participants at intervention/exposure
67 | Berge JM, Fertig AR, Trofholz A, e Brito JN. Real-time predictors of food parenting practices and child eating behaviors in racially/ethnically diverse families. Int J Behav Nutr Phys Act. Jul 11 2023;20(1):86. doi:10.1186/s12966-023-01476-4.37434195 | Outcome
68 | Berge JM, Meyer C, MacLehose RF, Loth K, Neumark-Sztainer D. Do Parents Treat Siblings Similarly or Differently with Regard to Feeding Practices, Weight-Related Conversations, and Support for Physical Activity? An Exploratory Analysis. Child Obes. Apr 2016;12(2):87–93. doi:10.1089/chi.2015.0049.26699095 | Study design
69 | Berge JM, Trofholz A, Tate AD, Examining unanswered questions about the home environment and childhood obesity disparities using an incremental, mixed-methods, longitudinal study design: The Family Matters study. Contemp Clin Trials. Nov 2017;62:61–76. doi: 10.1016/j.cct.2017.08.002.28800894 | Study design; Intervention/exposure
70 | Berge JM, Wall M, Bauer KW, Neumark-Sztainer D. Parenting characteristics in the home environment and adolescent overweight: a latent class analysis. Obesity (Silver Spring). Apr 2010;18(4):818–25. doi:10.1038/oby.2009.324.19816417 | Study design
71 | Berge JM, Wall M, Larson N, Forsyth A, Bauer KW, Neumark-Sztainer D. Youth dietary intake and weight status: healthful neighborhood food environments enhance the protective role of supportive family home environments. Health Place. Mar 2014;26:69–77. doi: 10.1016/j.healthplace.2013.11.007.24378461 | Study design
72 | Berkey CS, Rosner B, Willett WC, Tamimi RM, Lindsay Frazier A, Colditz GA. Prenatal factors and infant feeding in relation to risk of benign breast disease in young women. Breast Cancer Res Treat. Dec 2015;154(3):573–82. doi:10.1007/s10549-015-3637-3.26582399 | Outcome
73 | Bermudez de la Vega JA, Vazquez MA, Bernal S, Anthropometric, bone age, and bone mineral density changes after a family-based treatment for obese children. Calcif Tissue Int. Oct 2007;81(4):279–84. doi:10.1007/s00223-007-9071-8.17882344 | Study design; Intervention/exposure
74 | Berner N, Jay M, Lewis K, Hung W, Squires A, Ngai G. Comparison of parent and child versus child-only weight management interventions in the patient-centered medical home. Journal article. Journal of clinical outcomes management. 2015;22(2):57–60. | Intervention/exposure
75 | Berry DC, Schwartz TA, McMurray RG, The family partners for health study: a cluster randomized controlled trial for child and parent weight management. Nutr Diabetes. Jan 13 2014;4(1):e101. doi:10.1038/nutd.2013.42.24418827 | Intervention/exposure
76 | Best JR, Theim KR, Gredysa DM, Behavioral economic predictors of overweight children's weight loss. J Consult Clin Psychol. Dec 2012;80(6):1086–1096. doi:10.1037/a0029827.22924332 | Study design; Intervention/exposure
77 | Bhargava A, Jolliffe D, Howard LL. Socio-economic, behavioural and environmental factors predicted body weights and household food insecurity scores in the Early Childhood Longitudinal Study-Kindergarten. Br J Nutr. Aug 2008; 100(2):438–44. doi:10.1017/s0007114508894366.18275621 | Intervention/exposure
78 | Birch LL, Fisher JO. Mothers' child-feeding practices influence daughters' eating and weight. Am J Clin Nutr. 2000;71(5):1054–1061. doi:10.1093/ajcn/71.5.1054 10799366 | Study design
79 | Birch LL, Fisher JO, Davison KK. Learning to overeat: maternal use of restrictive feeding practices promotes girls' eating in the absence of hunger. Am J Clin Nutr. Aug 2003;78(2):215 20. doi:10.1093/ajcn/78.2.215.12885700 | Study design; Outcome
80 | Birch LL, Fisher JO, Grimm-Thomas K, Markey CN, Sawyer R, Johnson SL. Confirmatory factor analysis of the Child Feeding Questionnaire: a measure of parental attitudes, beliefs and practices about child feeding and obesity proneness. Appetite. Jun 2001;36(3):201–10. doi:10.1006/appe.2001.0398.11358344 | Study design
81 | Black MM, Hager ER, Wang Y, Toddler obesity prevention: A two-generation randomized attention-controlled trial. Matern Child Nutr. Jan 2021;17(1):e13075. doi:10.1111/mcn.13075.32885909 | Intervention/exposure
82 | Blaine RE, Fisher JO, Taveras EM, Reasons Low-Income Parents Offer Snacks to Children: How Feeding Rationale Influences Snack Frequency and Adherence to Dietary Recommendations. Nutrients. Jul 21 2015;7(7):5982–99. doi:10.3390/nu7075265.26197335 | Study design
83 | Blissett J, Farrow C. Predictors of maternal control of feeding at 1 and 2 years of age. Int J Obes (Lond). Oct 2007;31(10):1520–6. doi:10.1038/sj.ijo.0803661.17579636 | Outcome
84 | Blissett J, Haycraft E. Are parenting style and controlling feeding practices related? Appetite. Mar-May 2008;50(2–3):477–85. doi:10.1016/j.appet.2007.10.003. | Study design
85 | Bodnaruc AM, Kengneson CC, Blanchet R, Giroux I. Assessing the Validity and Reliability of a French Version of the Child Feeding Questionnaire among Black Mothers Living in Ottawa (Canada). Behav Sci (Basel). Jun 9 2023;13(6) doi:10.3390/bs13060487. | Study design
86 | Bogart LM, Elliott MN, Ober AJ, Home Sweet Home: Parent and Home Environmental Factors in Adolescent Consumption of Sugar-Sweetened Beverages. Acad Pediatr. Jul 2017;17(5):529–536. doi:10.1016/j.acap.2017.01.015.28143794 | Study design
87 | Bohnert AM, Randall ET, Tharp S, Germann J. The Development and Evaluation of a Portion Plate for Youth: A Pilot Study. Journal of Nutrition Education & Behavior. 2011;43(4):268–273. doi:10.1016/j.jneb.2010.07.007.21367664 | Study design; Intervention/exposure; Outcome
88 | Boles RE, Burdell A, Johnson SL, Gavin WJ, Davies PL, Bellows LL. Home food and activity assessment. Development and validation of an instrument for diverse families of young children. Appetite. Sep 2014;80:23–7. doi:10.1016/j.appet.2014.04.026.24798760 | Study design
89 | Boles RE, Reiter-Purtill J, Zeller MH. Persistently obese youth: interactions between parenting styles and feeding practices with child temperament. Clin Pediatr (Phila). Dec 2013;52(12):1098–106. doi:10.1177/0009922813497091.23884967 | Intervention/exposure; Outcome
90 | Boles RE, Scharf C, Filigno SS, Saelens BE, Stark LJ. Differences in home food and activity environments between obese and healthy weight families of preschool children. J Nutr Educ Behav. May-Jun 2013;45(3):222–31. doi:10.1016/j.jneb.2012.09.012.23380192 | Study design; Outcome
91 | Bonuck K, Avraham SB, Hearst M, Kahn R, Hyden C. Is overweight at 12 months associated with differences in eating behaviour or dietary intake among children selected for inappropriate bottle use? Matern Child Nutr. Apr 2014;10(2):234–44.. doi:10.1111/mcn.12042.23556429 | Study design; Intervention/exposure
92 | Boots SB, Tiggemann M, Corsini N, Mattiske J. Managing young children's snack food intake. The role of parenting style and feeding strategies. Appetite. Sep 2015;92:94–101. doi:10.1016/j.appet.2015.05.012.25982928 | Study design; Outcome
93 | Bost KK, Wiley AR, Fiese B, Hammons A, McBride B. Associations between adult attachment style, emotion regulation, and preschool children's food consumption. J Dev Behav Pediatr. Jan 2014;35(1):50–61. doi:10.1097/01.Dbp.0000439103.29889.18.24356497 | Publication status
94 | Boucher N. Feeding Styles and the Body Weight Status of Preschool-aged Children. Journal for Nurse Practitioners. 2014;10(4):234–239. | Study design
95 | Boucher NL. Feeding Style and a Child's Body Mass Index. J Pediatr Health Care. Nov-Dec 2016;30(6):583–589.. doi:10.1016/j.pedhc.2015.12.002.26833211 | Study design
96 | Boutelle KN, Cafri G, Crow SJ. Parent predictors of child weight change in family based behavioral obesity treatment. Obesity (Silver Spring). Jul 2012;20(7):1539–43. doi:10.1038/oby.2012.48.22421896 | Age of all participants at intervention/exposure
97 | Boutelle KN, Cafri G, Crow SJ. Parent-only treatment for childhood obesity: a randomized controlled trial. Obesity (Silver Spring). Mar 2011;19(3):574–80. doi:10.1038/oby.2010.238.20966907 | Intervention/exposure
98 | Boutelle KN, Fulkerson JA, Neumark-Sztainer D, Story M, French SA. Fast food for family meals: relationships with parent and adolescent food intake, home food availability and weight status. Public Health Nutr. Jan 2007;10(1):16–23. doi:10.1017/s136898000721794x.17212838 | Study design
99 | Boutelle KN, Kang Sim DE, Rhee KE, Manzano M, Strong DR. Family-based treatment program contributors to child weight loss. Int J Obes (Lond). Jan 2021;45(1):77–83. doi:10.1038/s41366-020-0604-9.32546860 | Age of all participants at intervention/exposure
100 | Boutelle KN, Zucker N, Peterson CB, Rydell S, Carlson J, Harnack LJ. An intervention based on Schachter's externality theory for overweight children: the regulation of cues pilot. J Pediatr Psychol. May 2014;39(4):405–17. doi:10.1093/jpepsy/jst142.24459240 | Intervention/exposure
101 | Braden A, Strong D, Crow S, Boutelle K. Parent changes in diet, physical activity, and behavior in family-based treatment for childhood obesity. Clin Pediatr (Phila). May 2015;54(5):494–7. doi:10.1177/0009922814538702.24928574 | Outcome; Age of all participants at intervention/exposure
102 | Brann LS, Skinner JD. More controlling child-feeding practices are found among parents of boys with an average body mass index compared with parents of boys with a high body mass index. J Am Diet Assoc. Sep 2005;105(9):1411–6. doi:10.1016/j.jada.2005.06.005.16129082 | Study design
103 | Branscum P, Lora K. Determinants of Parenting Practices Related to Monitoring Sugar Sweetened Beverages Among Hispanic Mothers. J Immigr Minor Health. Feb 2020;22(1):120–125. doi:10.1007/s10903-019-00875-9.30835031 | Study design
104 | Bravin Jl, Gutierrez AP, McCurley JL, Extra-familial social factors and obesity in the Hispanic Community Children's Health Study/Study of Latino Youth. J Behav Med. Oct 2019;42(5):947–959. doi:10.1007/s10865-019-00022-7.30911873 | Study design; Intervention/exposure
105 | Bravo P, Carcamo R, Santos S, Maternal sensitivity in early childhood and body mass index in adolescence: A population-based study on the role of self-regulation as a _mediator. Appetite. 2023;182:106418. doi:10.1016/j.appet.2022.106418 36521650 | Intervention/exposure
106 | Brazendale K, Beets MW, Turner-McGrievy GM, Kaczynski AT, Pate RR, Weaver RG. Children's Obesogenic Behaviors During Summer Versus School: A Within-Person Comparison. J Sch Health. Dec 2018;88(12):886–892. doi:10.1111/josh.12699.30392188 | Intervention/exposure
107 | Brennan L, Walkley J, Wilks R, Fraser SF, Greenway K. Physiological and behavioural outcomes of a randomised controlled trial of a cognitive behavioural lifestyle intervention for overweight and obese adolescents. Obes Res Clin Pract. Jan-Feb 2013;7(1):e23–41. doi:10.1016/j.orcp.2012.02.010.24331680 | Intervention/exposure
108 | Brewis A. Biocultural aspects of obesity in young Mexican schoolchildren. Am J Hum Biol. MayJun 2003;15(3):446–60. doi:10.1002/ajhb.10161.12704721 | Study design
109 | Broccoli S, Davoli AM, Albertini P, Motivational interviewing to treat overweight children and their parents in paediatrician's medical office: good results, but one year is not sufficient. Journal article. Epidemiologia e prevenzione. 2015;39(5–6):393.26554693 | Publication language
110 | Bronte-Tinkew J, Zaslow M, Capps R, Horowitz A, McNamara M. Food insecurity works through depression, parenting, and infant feeding to influence overweight and health in toddlers. J Nutr. Sep 2007; 137(9):2160–5. doi:10.1093/jn/137.9.2160.17709458 | Intervention/exposure
111 | Brophy S, Cooksey R, Gravenor MB, Risk factors for childhood obesity at age 5: analysis of the millennium cohort study. BMC Public Health. Dec 16 2009;9:467. doi: 10.1186/1471-2458-9-467.20015353 | Intervention/exposure
112 | Brophy-Herb HE, Martoccio TL, Kerver JM, Simply Dinner: A Randomized Controlled Trial of Home Meal Delivery. Academic pediatrics. 2022. | Intervention/exposure
113 | Brown A, Lee MD. Early influences on child satiety-responsiveness: the role of weaning style. Pediatr Obes. 2015;10(1):57–66. doi:10.1111/j.2047-6310.2013.00207.x 24347496 | Age of all participants at intervention/exposure
114 | Brown A. Maternal restraint and external eating behaviour are associated with formula use or shorter breastfeeding duration. Appetite. May 2014;76:30–5. doi:10.1016/j.appet.2013.12.022.24463067 | Study design; Outcome
115 | Brown CL, Pratt K, Martin S, Hulshult H, Skelton JA. Weight Control Practices in Children of Parents Participating in Weight Management Programs. Child Obes. Oct 2019;15(7):451–458. doi:10.1089/chi.2019.0089.31343259 | Study design
116 | Brown KA, Ogden J, Vogel C, Gibson EL. Corrigendum to "The role of parental control practices in explaining children's diet and BMI" [Appet. 50 (2008) 252–259]. Appetite. Jan 1 2017;108:525. doi:10.1016/j.appet.2016.11.035.27916193 | Publication status
117 | Bryant M, Stevens J, Wang L, Tabak R, Borja J, Bentley ME. Relationship between home fruit and vegetable availability and infant and maternal dietary intake in African-American families: evidence from the exhaustive home food inventory. J Am Diet Assoc. 2011;111(10): 1491–1497. doi:10.1016/j.jada.2011.07.007 21963015 | Study design
118 | Brzezinski M, Korzeniowska K, Szarejko K, APoZdrola as an example of a successful multicenter programme for obesity management and healthy lifestyle promotion in children and adolescents-programme protocol and preliminary results from the first intervention site. Pediatr Endocrinol Diabetes Metab. 2020;26(1):22–26. doi:10.5114/pedm.2020.94393 32418419 | Intervention/exposure
119 | Buch-Andersen T, Eriksson F, Bloch P, Glumer C, Mikkelsen BE, Toft U. The Danish SoL Project: Effects of a Multi-Component Community-Based Health Promotion Intervention on Prevention of Overweight among 3–8-Year-Old Children. Int J Environ Res Public Health. Aug 9 2021;18(16). doi:10.3390/ijerph18168419. | Intervention/exposure
120 | Bucher Della Torre S, Dudley-Martin F, Kruseman M. 'Croque&bouge': A feasible and acceptable programme for obesity prevention in preschoolers at risk and their parents. SAGE Open Med. 2015;3:2050312115574365. doi:10.1177/2050312115574365.26770769 | Study design; Intervention/exposure; Outcome
121 | Buchmann AF, Kopf D, Westphal S, Impact of early parental child-rearing behavior on young adults' cardiometabolic risk profile: a prospective study. Psychosom Med. Feb 2010;72(2):156–62. doi:10.1097/PSY.0b013e3181c88343.19995883 | Intervention/exposure
122 | Budge M, Sharifi M, Maciejewski KR, A Mixed-Methods Analysis of a Special Supplemental Nutrition Program for Women, Infants, and Children and Primary Care Partnership to Promote Responsive Feeding for Infants in Group Well-Child Care. Acad Pediatr. Mar 2023;23(2):304–313. doi:10.1016/j.acap.2022.12.017.36599376 | Intervention/exposure
123 | Burdette HL, Whitaker RC, Hall WC, Daniels SR. Maternal infant-feeding style and children's adiposity at 5 years of age. Arch Pediatr Adolesc Med. May 2006; 160(5):513–20. doi:10.1001/archpedi.160.5.513.16651495 | Age of all participants at intervention/exposure
124 | Burnett AJ, Lamb KE, Spence AC, Lacy KE, Worsley A. Parenting style as a predictor of dietary score change in children from 4 to 14 years of age. Findings from the Longitudinal Study of Australian Children. Public Health Nutr. Dec 2021;24(18):6058–6066. doi: 10.1017/s1368980021003062.34296665 | Outcome
125 | Burnett AJ, Jansen E, Appleton J, Bidirectional associations between parental feeding practices, infant appetitive traits and infant BMIz: a longitudinal cohort study. International Journal of Behavioral Nutrition & Physical Activity. 2022;19(1):1–11. doi: 10.1186/s12966-022-01392-z.34991593 | Age of all participants at intervention/exposure
126 | Burrows T, Warren JM, Collins CE. The impact of a child obesity treatment intervention on parent child-feeding practices. Int J Pediatr Obes. 2010;5(1):43–50. doi:10.3109/17477160902957158.19437180 | Age of all participants at intervention/exposure
127 | Buscemi J, Berlin KS, Rybak TM, Health Behavior and Weight Changes Among Ethnic and Racial Minority Preschoolers and Their Parents: Associations Across 1 Year. J Pediatr Psychol. Aug 2016;41(7):777–85. doi:10.1093/jpepsy/jsv165.26717958 | Intervention/exposure; Outcome
128 | Butte NF. Impact of infant feeding practices on childhood obesity. J Nutr. Feb 2009;139(2):412s 6s. doi:10.3945/jn.108.097014.19106326 | Study design
129 | Button A, Faith MS, Paluch RA, Kong KL. Interplay between Prepregnancy Body Mass Index, Early Childhood Negative Temperament, and Slowness in Eating on Early Childhood Rapid Weight Gain. Child Obes. Jul 1 2021. doi:10.1089/chi.2021.0024. | Intervention/exposure
130 | Byely L, Archibald AB, Graber J, Brooks-Gunn J. A prospective study of familial and social influences on girls' body image and dieting. Int J Eat Disord. Sep 2000;28(2):155–64.. doi:10.1002/1098-108x(200009)28:2<155::aid-eat4>3.0.co;2-k.10897077 | Intervention/exposure
131 | Byrd-Bredbenner C, Abbot JM, Cussler E. Mothers of young children cluster into 4 groups based on psychographic food decision influencers. Nutr Res. Aug 2008;28(8):506–16.. doi: 10.1016/j.nutres.2008.05.012.19083453 | Study design; Intervention/exposure
132 | Byrd-Bredbenner C, Martin-Biggers J, Povis GA, Worobey J, Hongu N, Quick V. Promoting healthy home environments and lifestyles in families with preschool children: HomeStyles, a randomized controlled trial. Contemp Clin Trials. Jan 2018;64:139–151. doi:10.1016/j.cct.2017.10.012.29079392 | Intervention/exposure
133 | Byrne R, Jansen E, Daniels L. Perceived fussy eating in Australian children at 14 months of age and subsequent use of maternal feeding practices at 2 years. Int J Behav Nutr Phys Act. Sep 11 2017;14(1):123. doi:10.1186/s12966-017-0582-z.28893283 | Intervention/exposure
134 | Calamaro CJ, Faith MS. Preventing childhood overweight. Nutrition Today. 2004;39(5):194–199. | Publication status
135 | Camci N, Bas M, Buyukkaragoz AH. The psychometric properties of the Child Feeding Questionnaire (CFQ) in Turkey. Article. Appetite. 2014;78:49–54.24656946 | Study design
136 | Cameron AJ, Ball K, Hesketh KD, Variation in outcomes of the Melbourne Infant, Feeding, Activity and Nutrition Trial (InFANT) Program according to maternal education and age. Prev Med. Jan 2014;58:58–63. doi:10.1016/j.ypmed.2013.10.021.24201090 | Intervention/exposure
137 | Campbell K, Hesketh K, Crawford D, Salmon J, Ball K, McCallum Z. The Infant Feeding Activity and Nutrition Trial (INFANT) an early intervention to prevent childhood obesity: clusterrandomised controlled trial. BMC Public Health. Mar 31 2008;8:103. doi: 10.1186/1471-2458-8-103.18373877 | Study design; Publication status
138 | Campos J, Cochran L, Rubin D, Adjo J. CULTURALLY SENSITIVE NUTRITION INTERVENTION FOR CHILDREN OF DOMINICAN HERITAGE WITH OBESITY. Journal article; Conference proceeding. Journal of investigative medicine. 2022;70(4):1019–1020. | Publication status
139 | Carbonneau N, Carbonneau E, Dumas AA, Lavigne G, Guimond FA. Examining the associations between mothers' motivation to regulate their own eating behaviors, food parenting practices and perceptions of their child's food responsiveness. Appetite. Jun 1 2023;185:106514. doi:10.1016/j.appet.2023.106514.36905988 | Study design
140 | Cardel M, Dulin-Keita A, Casazza K. Contributors to Pediatric Obesity in Adolescence: More than just Energy Imbalance. Open Obes J. 2011;3(2):17–26. doi:10.2174/1876823701103010017.24563683 | Publication status
141 | Cardel M, Willig AL, Dulin-Keita A, Casazza K, Beasley TM, Fernandez JR. Parental feeding practices and socioeconomic status are associated with child adiposity in a multi-ethnic sample of children. Appetite. Feb 2012;58(1):347–53. doi:10.1016/j.appet.2011.11.005.22100186 | Study design
142 | Carlson JA, Crespo NC, Sallis JF, Patterson RE, Elder JP. Dietary-related and physical activityrelated predictors of obesity in children: a 2-year prospective study. Child Obes. Apr 2012;8(2):110–5. doi:10.1089/chi.2011.0071.22799510 | Age of all participants at intervention/exposure
143 | Cartagena D, McGrath JM, Masho SW. Differences in modifiable feeding factors by overweight status in Latino infants. Appl Nurs Res. May 2016;30:210–5. doi:10.1016/j.apnr.2015.09.005.27091280 | Study design
144 | Cebeci AN, Guven A. Does maternal obesity have an influence on feeding behavior of obese children? Minerva Pediatr. Dec 2015;67(6):481–7.25034219 | Study design
145 | Celia S, lannaccone M, Cotrufo P. How perceived parental bonding affects self-concept and drive for thinness: a community-based study. Eat Behav. Jan 2014;15(1):110–5. doi: 10.1016/j.eatbeh.2013.10.024.24411762 | Study design; Intervention/exposure
146 | Chaidez V, Kaiser LL. Validation of an instrument to assess toddler feeding practices of Latino mothers. Appetite. Aug 2011;57(1):229–36. doi:10.1016/j.appet.2011.05.106.21600943 | Study design; Outcome
147 | Chaidez V, McNiven S, Vosti SA, Kaiser LL. Sweetened food purchases and indulgent feeding are associated with increased toddler anthropometry. J Nutr Educ Behav. Jul-Aug 2014;46(4):293–298. doi:10.1016/j.jneb.2013.05.011.24188800 | Age of all participants at intervention/exposure
148 | Chan JC, Sobal J. Family meals and body weight. Analysis of multiple family members in family units. Appetite. Oct 2011;57(2):517–24. doi: 10.1016/j.appet.2011.07.001.21763740 | Study design
149 | Chan L, Magarey AM, Daniels LA. Maternal feeding practices and feeding behaviors of Australian children aged 12–36 months. Matern Child Health J. Nov 2011;15(8):1363–71. doi:10.1007/s10995-010-0686-4.20872057 | Study design; Outcome
150 | Chang Y, Halgunseth LC. The association between family meals and early-adolescents' weight status change in the context of parental discipline practices: the moderating roles of ethnicity and acculturation. J Immigr Minor Health. Apr 2015;17(2):450–8. doi: 10.1007/s10903-014-0084-x.25138136 | Age of all participants at intervention/exposure
151 | Cheah CS, Van Hook J. Chinese and Korean immigrants' early life deprivation: an important factor for child feeding practices and children's body weight in the United States. Soc Sci Med. Mar 2012;74(5):744–52. doi:10.1016/j.socscimed.2011.10.040.22265872 | Study design
152 | Chee Din MA, Mohd Fahmi Teng Nl, Abdul Manaf Z. Maternal depression and child feeding practices: Determinants to malnutrition among young children in Malaysian rural area. Article. Women's Health. 2023;19 doi: 10.1177/17455057221147800. | Study design; Intervention/exposure
153 | Chen D, Jaenicke EC, Volpe RJ. The Healthfulness of Food-at-Home Expenditures, the Local Food Environment, and Childhood Obesity. Am J Health Promot. Mar 2019;33(3):412–419. doi:10.1177/0890117118786871.30004249 | Intervention/exposure
154 | Chen J, Weiss S, Heyman MB, Cooper B, Lustig RH. The Efficacy of the Web-Based Childhood Obesity Prevention Program in Chinese American Adolescents (Web ABC Study). Journal article. Journal of adolescent health. 2011;49(2):148–154. | Intervention/exposure
155 | Chen JL, Kwan M. Short-Term Efficacy and Correlates of Change in Health Weight Management Program for Chinese American Children. Clin Pediatr (Phila). May 2016;55(5):463 9. doi:10.1177/0009922815592608.26149851 | Intervention/exposure
156 | Chen T-L, Chen Y-Y, Lin C-L, Peng F-S, Chien L-Y. Responsive Feeding, Infant Growth, and Postpartum Depressive Symptoms during 3 Months Postpartum. Nutrients. 2020; 12(6):1766. doi:10.3390/nu12061766.32545540 | Study design
157 | Chew CSE, Kelly SM, Rajasegaran K, Three month outcome of a family based intervention program for adolescent obesity: the LITE randomised controlled trial. Journal article; Conference proceeding. Obesity reviews. 2016;17:124. | Publication status
158 | Chiang ES, Padilla MA. Assessment of Parent Orientation towards Autonomy vs. Control in Promoting Children's Healthy Eating and Exercise. Appl Psychol Health Well Being. Jul 2012;4(2):202–17. doi:10.1111/j.1758-0854.2012.01069.x.26286978 | Study design; Intervention/exposure
159 | Chiong R, Gray VB, Roy R. Development of a Family-Based Nutrition Program Rooted in Food Parenting Literature. Fam Consum Sci Res J. Sep 2020;49(1):67–83.33239856 | Intervention/exposure; Outcome
160 | Choi MJ, Kang H, Choi J. Risk Factors for Obesity in Five-Year-Old Children: Based on Korean National Health Insurance Service (NHIS) Data. Article. Children. 2022;9(3) doi:10.3390/children9030314. | Study design
161 | Chomitz VR, Park HJ, Weser S, Modifying dietary risk behaviors to prevent obesity and dental caries in very young children: results of the Baby Steps to Health pediatric dental pilot. Journal of Public Health Dentistry. Fall2019 2019;79(3):207–214. doi:10.1111/jphd.12311.30801726 | Outcome
162 | Chu L, Retnakaran R, Zinman B, Hanley AJG, Hamilton JK. Impact of maternal physical activity and infant feeding practices on infant weight gain and adiposity. Article. International Journal of Endocrinology. 2012. | Intervention/exposure
163 | Clavenna A, Morabito E, Cartabia M, Campi R, Pandolfini CL, Bonati M. National, longitudinal NASCITA birth cohort study: prevalence of overweight at 12 months of age in children born healthy. BMJ Paediatr Open. Jan 2023;7(1) doi:10.1136/bmjpo-2022-001622. | Study design; Intervention/exposure
164 | Cohen E, Richter LM, Chidumwa G, Relationships Between Maternal Factors and Weight Loss Attempts Among Urban Male and Female Adolescents Living in Soweto, Johannesburg, South Africa. J Adolesc Health. Jan 2020;66(1s):S17–s24. doi:10.1016/j.jadohealth.2019.10.015.31866033 | Intervention/exposure
165 | Conlon BA, McGinn AP, Lounsbury DW, The Role of Parenting Practices in the Home Environment among Underserved Youth. Child Obes. Aug 2015;11(4):394–405. doi:10.1089/chi.2014.0093.26258561 | Study design
166 | Consales A, Morniroli D, Vizzari G, Mosca F, Giannì ML. Nutrition for Infant Feeding. Nutrients. 2022;14(9):1823–1823. doi:10.3390/nu14091823.35565790 | Intervention/exposure; Publication status
167 | Contento IR, Zybert P, Williams SS. Relationship of cognitive restraint of eating and disinhibition to the quality of food choices of Latina women and their young children. Prev Med. 2005;40:326.15533547 | Study design; Intervention/exposure
168 | Cooke MJ, Wilk P, Paul KW, Gonneville SL. Predictors of obesity among Métis children: socioeconomic, behavioural and cultural factors. Can J Public Health. Jun 21 2013;104(4):e298–303. doi:10.17269/cjph.104.3765.24044469 | Study design; Intervention/exposure
169 | Corsini N, Wilson C, Kettler L, Danthiir V. Development and preliminary validation of the Toddler Snack Food Feeding Questionnaire. Appetite. Jun 2010;54(3):570–8. doi:10.1016/j.appet.2010.03.001.20211670 | Study design
170 | Costa A, Hetherington MM, Oliveira A. Maternal perception, concern and dissatisfaction with child weight and their association with feeding practices in the Generation XXI birth cohort. Br J Nutr. 2022;127(7):1106–1116. doi:10.1017/S0007114521001653 34016202 | Outcome
171 | Costa A, Oliveira A. Parental Feeding Practices and Children's Eating Behaviours: An Overview of Their Complex Relationship. Healthcare (2227–9032). 2023;11(3):400. doi:10.3390/healthcare11030400.36766975 | Study design
172 | Costa FS, Pino DL, Friedman R. Caregivers' attitudes and practices: influence on childhood body weight. J Biosoc Sci. May 2011;43(3):369–78. doi:10.1017/s0021932011000022.21306663 | Study design
173 | Cottrell L, Harris CV, Bradlyn A, Identifying the people and factors that influence children's intentions to make lifestyle changes. Health Promot Pract. Mar 2012;13(2):183–9. doi:10.1177/1524839910384053.21343422 | Study design
174 | Couch SC, Glanz K, Zhou C, Sallis JF, Saelens BE. Home food environment in relation to children's diet quality and weight status. J Acad Nutr Diet. Oct 2014;114(10):1569–1579.e1. doi:10.1016/j.jand.2014.05.015.25066057 | Study design
175 | Coulthard H, Van den Tol AJM, Jeffers S, Ryan S. Music as an alternative self-regulation strategy to snack foods following a negative mood induction in 5–7-year-old children: Interactions with parental use of food as a reward. Appetite. Jul 1 2023;186:106517. doi:10.1016/j.appet.2023.106517.36863533 | Outcome
176 | Crespo NC, Elder JP, Ayala GX, Results of a multi-level intervention to prevent and control childhood obesity among Latino children: the Aventuras Para Niños Study. Ann Behav Med. Feb 2012;43(1):84–100. doi:10.1007/s12160-011-9332-7.22215470 | Intervention/exposure
177 | Cromley T, Neumark-Sztainer D, Story M, Boutelle KN. Parent and family associations with weight-related behaviors and cognitions among overweight adolescents. J Adolesc Health. Sep 2010;47(3):263–9. doi:10.1016/j.jadohealth.2010.02.009.20708565 | Study design; Intervention/exposure
178 | Crouch P, O'Dea JA, Battisti R. Child feeding practices and perceptions of childhood overweight and childhood obesity risk among mothers of preschool children. Nutrition & Dietetics. 2007;64(3):151–158. | Study design
179 | Crowell MD, Murphy TB, Levy RL, Eating behaviors and quality of life in preadolescents at risk for obesity with and without abdominal pain. J Pediatr Gastroenterol Nutr. Feb 2015;60(2):217–23. doi:10.1097/mpg.0000000000000585.25272321 | Study design; Intervention/exposure
180 | Cummings JR, Faith MS, Lipsky LM, Liu A, Mooney JT, Nansel TR. Prospective relations of maternal reward-related eating, pregnancy ultra-processed food intake and weight indicators, and feeding mode with infant appetitive traits. Int J Behav Nutr Phys Act. 2022;19(1):100. Published 2022 Aug 3. doi:10.1186/s12966-022-01334-9 35922793 | Intervention/exposure; Outcome
181 | Cunningham-Sabo L, Lohse B, Smith S, Fuel for Fun: a cluster-randomized controlled study of cooking skills, eating behaviors, and physical activity of 4th graders and their families. BMC Public Health. May 26 2016;16:444. doi:10.1186/s12889-016-3118-6.27230565 | Study design; Intervention/exposure
182 | Cynthia J, Zalilah MS, Lim MY. Relationship between family meals away from home and nutritional status of adolescents. Malays J Nutr. Apr 2013;19(1):25–35.24800382 | Study design
183 | Czaja J, Hartmann AS, Rief W, Hilbert A. Mealtime family interactions in home environments of children with loss of control eating. Appetite. Jun 2011;56(3):587–93. doi:10.1016/j.appet.2011.01.030.21291929 | Study design; Outcome
184 | Dahill LM, Morrison NMV, Mannan H, Exploring associations between positive and negative valanced parental comments about adolescents' bodies and eating and eating problems: a community study. J Eat Disord. Mar 24 2022;10(1):43. doi:10.1186/s40337-022-00561-6.35331338 | Study design
185 | Daniels L, Mallan K, Nicholson J, Meedeniya J, Magarey A. Child behaviour and weight outcomes of NOURISH RCT. Journal article; Conference proceeding. Obesity facts. 2013;6:16. | Outcome
186 | Daniels L, Mallan K, Nicholson J, Thorpe K, Magarey A. Longer term child growth and maternal feeding practices outcomes of the NOURISH obesity prevention trial. Journal article; Conference proceeding. Obesity facts. 2014;7:39. | Publication status
187 | Daniels LA, Mallan KM, Battistutta D, Child eating behavior outcomes of an early feeding intervention to reduce risk indicators for child obesity: the NOURISH RCT. Obesity (Silver Spring). May 2014;22(5):E104–11.24415390 | Outcome
188 | Daniels LA, Mallan KM, Battistutta D, Nicholson JM, Perry R, Magarey A. Evaluation of an intervention to promote protective infant feeding practices to prevent childhood obesity: outcomes of the NOURISH RCT at 14 months of age and 6 months post the first of two intervention modules. Int J Obes (Lond). Oct 2012;36(10):1292–8. doi:10.1038/ijo.2012.96.22710926 | Age of all participants at intervention/exposure
189 | Daniels LA, Mallan KM, Nicholson JM, Battistutta D, Magarey A. Outcomes of an early feeding practices intervention to prevent childhood obesity. Pediatrics. Jul 2013;132(1):e109–18. doi:10.1542/peds.2012-2882.23753098 | Age of all participants at intervention/exposure
190 | Daniels LA, Mallan KM, Nicholson JM, An Early Feeding Practices Intervention for Obesity Prevention. Pediatrics. Jul 2015;136(1):e40–9. doi:10.1542/peds.2014-4108.26055848 | Age of all participants at intervention/exposure
191 | Daniels SR. Child feeding practices and obesity. Article. Journal of Pediatrics. 2006;148(3):A1. | Publication status
192 | Datar A, Shier V, Liu Y. Understanding drivers of micro-level disparities in childhood body mass index, overweight, and obesity within low-income, minority communities. Prev Med Rep. Apr 2023;32:102143. doi:10.1016/j.pmedr.2023.102143.36875513 | Study design
193 | Davis KE, Klingenberg A, Massey-Stokes M, The Baby Bites Text Messaging Project with randomized controlled trial: texting to improve infant feeding practices. Mhealth. 2023;9:11. doi:10.21037/mhealth-22-31.37089270 | Study design; Intervention/exposure
194 | Davis SM, Myers OB, Cruz TH, CHILE: Outcomes of a group randomized controlled trial of an intervention to prevent obesity in preschool Hispanic and American Indian children. Prev Med. Aug 2016;89:162–168. doi:10.1016/j.ypmed.2016.05.018.27222162 | Intervention/exposure
195 | Davison KK, Lawson HA, Coatsworth JD. The Family-centered Action Model of Intervention Layout and Implementation (FAMILI): the example of childhood obesity. Health Promot Pract. Jul 2012;13(4):454–61. doi:10.1177/1524839910377966.21632465 | Study design
196 | Dawson-McClure S, Brotman LM, Theise R, Early childhood obesity prevention in low-income, urban communities. J Prev Interv Community. 2014;42(2):152–66. doi:10.1080/10852352.2014.881194.24702665 | Study design; Intervention/exposure
197 | de Barse LM, Tharner A, Micali N, Does maternal history of eating disorders predict mothers' feeding practices and preschoolers' emotional eating? Appetite. Feb 2015;85:1–7. doi:10.1016/j.appet.2014.10.031.25450896 | Intervention/exposure; Outcome
198 | De Bourdeaudhuij I, Verbestel V, De Henauw S, Behavioural effects of a community-oriented setting-based intervention for prevention of childhood obesity in eight European countries. Main results from the IDEFICS study. Obes Rev. Dec 2015;16 Suppl 2:30–40. doi:10.1111/obr.12347.26707014 | Intervention/exposure
199 | de Campora G, Giromini L, Guerriero V, Chiodo C, Zavattini GC, Larciprete G. Influence of maternal reflective functioning on mothers' and children's weight: A follow-up study. Infant Ment Health J. Nov 2019;40(6):862–873. doi:10.1002/imhj.21819.31392750 | Intervention/exposure
200 | De Henauw S, Huybrechts I, De Bourdeaudhuij I, Effects of a community-oriented obesity prevention programme on indicators of body fatness in preschool and primary school children. Main results from the IDEFICS study. Obes Rev. Dec 2015;16 Suppl 2:16–29. doi:10.1111/obr.12346.26707013 | Intervention/exposure
201 | De Silva DA, Thoma ME. Maternal Food Insecurity and Early Childhood Obesity: A Sex-Specific Response? Annals of Epidemiology. 2020;49:75–75. | Publication status
202 | de Winter AF, Visser L, Verhulst FC, Vollebergh WA, Reijneveld SA. Longitudinal patterns and predictors of multiple health risk behaviors among adolescents: The TRAILS study. Prev Med. Mar 2016;84:76–82. doi:10.1016/j.ypmed.2015.11.028.26656404 | Intervention/exposure
203 | Deal BJ, Huffman MD, Binns H, Stone NJ. Perspective: Childhood Obesity Requires New Strategies for Prevention. Adv Nutr. Sep 1 2020;11(5):1071–1078. doi:10.1093/advances/nmaa040.32361757 | Study design
204 | Decaluwé V, Braet C, Moens E, Van Vlierberghe L. The association of parental characteristics and psychological problems in obese youngsters. Int J Obes (Lond). Dec 2006;30(12):1766–74. doi:10.1038/sj.ijo.0803336.16607384 | Study design
205 | DeCator DD, Carter JS, Schneider KL. Brief report: Family meals, obesogenic factors, and depressive symptoms in youth. Article. Mental Health and Physical Activity. 2016;10:1–3. | Outcome
206 | Decker JW. Initial development and testing of a questionnaire of parental self-efficacy for enacting healthy lifestyles in their children. J Spec Pediatr Nurs. Apr 2012;17(2):147–58. doi:10.1111/j.1744-6155.2012.00330.x.22463475 | Study design; Intervention/exposure; Outcome
207 | De-Jongh González O, Tugault-Lafleur CN, O'Connor TM, Hughes SO, Mâsse LC. Are fathers' and mothers' food parenting practices differentially associated with children's eating behaviors? Appetite. Nov 1 2021;166:105434. doi:10.1016/j.appet.2021.105434.34107293 | Study design; Outcome; Age of all participants at intervention/exposure
208 | Del Valle C, Miranda H, Orellana L, Grunert KG, Schnettler B. Measurement invariance of the comprehensive feeding practices questionnaire in dual-earner parents with adolescent children in Chile. Front Psychol. 2022; 13:1031391. doi:10.3389/fpsyg.2022.1031391.36687991 | Study design
209 | De Delaney CL, Byrd-Bredbenner C. Family Social Support and Weight-Related Behaviors of School-Age Children: An Exploratory Analysis. Int J Environ Res Public Health. Jul 12 2022;19(14) doi:10.3390/ijerph19148501. | Outcome; Age of all participants at intervention/exposure
210 | Delisle Nystrom C, Sandin S, Henriksson P, Henriksson H, Maddison R, Lof M. A 12-month follow-up of a mobile-based (mHealth) obesity prevention intervention in pre-school children: the MINISTOP randomized controlled trial. BMC Public Health. May 24 2018;18(1):658. doi:10.1186/s12889-018-5569-4.29793467 | Intervention/exposure
211 | Delisle C, Sandin S, Forsum E, A web- and mobile phone-based intervention to prevent obesity in 4-year-olds (MINISTOP): a population-based randomized controlled trial. BMC Public Health. Feb 7 2015;15:95. doi:10.1186/s12889-015-1444-8.25886009 | Study design; Intervention/exposure
212 | DeLong AJ, Larson Nl, Story M, Neumark-Sztainer D, Weber-Main AM, Ireland M. Factors associated with overweight among urban American Indian adolescents: findings from Project EAT. Ethn Pis. Summer 2008; 18(3):317–23. | Study design
213 | Derks IPM, Bolhuis K, Sijbrands EJG, Gaillard R, Hillegers MHJ, Jansen PW. Predictors and patterns of eating behaviors across childhood: Results from The Generation R study. Appetite. Oct 1 2019;141:104295. doi:10.1016/j.appet.2019.05.026.31128200 | Intervention/exposure; Outcome
214 | Derks IPM, Sijbrands EJG, Wake M, Eating behavior and body composition across childhood: a prospective cohort study. Int J Behav Nutr Phys Act. Oct 1 2018;15(1):96. doi:10.1186/s12966-018-0725-x.30285789 | Intervention/exposure
215 | Derwig M, Tiberg I, Bjork J, Kristensson Hallstrom I. Changes in perceived parental self-efficacy after a Child-Centred Health Dialogue about preventing obesity. Article. Acta Paediatrica, International Journal of Paediatrics. 2022;111(10):1956–1965. doi:10.1111/apa.16453. | Intervention/exposure
216 | Dev DA, McBride BA, Fiese BH, Jones BL, Cho H. Risk factors for overweight/obesity in preschool children: an ecological approach. Child Obes. Oct 2013;9(5):399–408. doi:10.1089/chi.2012.0150.24020790 | Study design
217 | Dhuper S, Bayoumi N, Dalvi J, Panzer B. The Correlation Between Parental Perceptions and Readiness to Change with Participation in a Pediatric Obesity Program Serving a Predominantly Black Urban Community: A Retrospective Cohort Study. Matern Child Health J. Apr 2021;25(4):606–612. doi:10.1007/s10995-020-03058-3.33237508 | Intervention/exposure
218 | Dinkevich E, Leid L, Pryor K, Wei Y, Huberman H, Carnell S. Mothers' feeding behaviors in infancy: Do they predict child weight trajectories? Obesity (Silver Spring). Dec 2015;23(12):2470–6. doi:10.1002/oby.21320.26537027 | Age of all participants at intervention/exposure
219 | Dixon RS, Gill JM, Adair VA. Exploring paternal influences on the dieting behaviors of adolescent girls. Eat Disord. Spring 2003;11(1):39–50. doi:10.1080/10640260390167474. | Study design; Intervention/exposure; Outcome
220 | Do B, Yang CH, Lopez NV, Mason TB, Margolin G, Dunton GF. Investigating the momentary association between maternal support and children's fruit and vegetable consumption using ecological momentary assessment. doi:10.1016/j.appet.2020.104667. | Study design; Outcome; Age of all participants at intervention/exposure
221 | Dogan E, Yilmaz G, Caylan N, Turgut M, Gokcay G, Oguz MM. Baby-led complementary feeding: Randomized controlled study. Pediatrics International. 2018;60(12):1073–1080. doi:10.1111/ped.13671.30074671 | Age of all participants at intervention/exposure
222 | Donnelly R, Marteleto LJ. Gender, Socioeconomic Status, and Diet Behaviors within Brazilian Families. Socius. Jan-Dec 2018;4. doi:10.1177/2378023118804688. | Study design
223 | Doorley E, Young C, O'Shea B, Darker C, Hollywood B, O'Rorke C. Is primary prevention of childhood obesity by education at 13-month immunisations feasible and acceptable? Results from a general practice based pilot study. Ir Med J. Jan 2015;108(1):13–5.25702347 | Intervention/exposure; Outcome
224 | Dorosty AR, Emmett PM, Cowin IS, Reilly JJ. Factors associated with early adiposity rebound. Pediatrics. 2000;105(5):1115–1118.10790472 | Intervention/exposure
225 | Dos Santos CT, Machado CO, Hofelmann DA. Family meals, diet quality and obesity among adolescents: findings from a school-based study in a capital city of southern Brazil. Minerva Pediatr (Torino). Apr 2 2021; doi:10.23736/s2724-5276.20.05918-6. | Study design
226 | Drapeau V, Harvey AA, Jacob R, Provencher V, Panahi S. The impact of a family web-based nutrition intervention to increase fruit, vegetable, and dairy intakes: a single-blinded randomized family clustered intervention. Nutr J. Dec 20 2022;21(1):75. doi:10.1186/s12937-022-00825-6.36539753 | Intervention/exposure
227 | Dreimane D, Safani D, MacKenzie M, Feasibility of a hospital-based, family-centered intervention to reduce weight gain in overweight children and adolescents. Diabetes Res Clin Pract. Feb 2007;75(2): 159–68. doi:10.1016/j.diabres.2006.05.017.16837096 | Intervention/exposure
228 | Drenowatz C, Kobel S, Kettner S, Correlates of weight gain in German children attending elementary school. Prev Med. Oct 2013;57(4):310–4. doi:10.1016/j.ypmed.2013.06.004.23769901 | Intervention/exposure
229 | Dubuisson AC, Zech FR, Dassy MM, Jodogne NB, Beauloye VM. Determinants of weight loss in an interdisciplinary long-term care program for childhood obesity. ISRN Obes. 2012;2012:349384.. doi:10.5402/2012/349384.24527260 | Intervention/exposure
230 | Duncan S, Duncan EK, Fernandes RA, Modifiable risk factors for overweight and obesity in children and adolescents from São Paulo, Brazil. BMC Public Health. Jul 22 2011;11:585. doi:10.1186/1471-2458-11-585.21781313 | Study design
231 | Duncanson K, Burrows TL, Collins CE. Child Feeding and Parenting Style Outcomes and Composite Score Measurement in the 'Feeding Healthy Food to Kids Randomised Controlled Trial'. Children (Basel). 2016;3(4):28. Published 2016 Nov 10. doi:10.3390/children3040028 27834906 | Outcome
232 | Dunton GF, Ke W, Dzubur E, O'Connor SG, Lopez NV, Margolin G. Within-Subject Effects of Stress on Weight-Related Parenting Practices in Mothers: An Ecological Momentary Assessment Study. Ann Behav Med. Mar 28 2019;53(5):415–425. doi:10.1093/abm/kay053.31222228 | Intervention/exposure; Outcome
233 | Eagleton SG, Hohman EE, Verdiglione N, Birch LL, Paul IM, Savage JS. INSIGHT Study Maternal Return to Work and Infant Weight Outcomes. Acad Pediatr. Jan-Feb 2019;19(1):67–73. doi:10.1016/j.acap.2018.08.008.30145361 | Intervention/exposure
234 | Edwards AC, Jacobson SW, Senekal M, Fetal Alcohol-Related Postnatal Growth Restriction Is Independent of Infant Feeding Practices and Postnatal Alcohol Exposure in a Prospective South African Birth Cohort. Article. Nutrients. 2023;15(9) doi:10.3390/nu15092018. | Intervention/exposure
235 | Ek A, Sorjonen K, Nyman J, Marcus C, Nowicka P. Child behaviors associated with childhood obesity and parents' self-efficacy to handle them: confirmatory factor analysis of the Lifestyle Behavior Checklist. Int J Behav Nutr Phys Act. 2015;12:36.25889819 | Study design; Outcome
236 | Ek A, Delisle Nystrom C, Chirita-Emandi A, A randomized controlled trial for overweight and obesity in preschoolers: the More and Less Europe study - an intervention within the STOP project. BMC Public Health. Jul 15 2019;19(1):945. doi:10.1186/s12889-019-7161-y.31307412 | Study design
237 | Elias CV, Power TG, Beck AE, Depressive Symptoms and Perceptions of Child Difficulty Are Associated with Less Responsive Feeding Behaviors in an Observational Study of Low-Income Mothers. Child Obes. Dec 2016;12(6):418–425. doi:10.1089/chi.2016.0125.27662419 | Study design; Outcome
238 | El-Sayed H, Martines J, Rakha M, Zekry O, Abdel-Hak M, Abbas H. The effectiveness of the WHO training course on complementary feeding counseling in a primary care setting, Ismailia, Egypt. J Egypt Public Health Assoc. Apr 2014;89(1):1–8. doi:10.1097/01.EPX.0000443990.46047.a6.24717394 | Intervention/exposure
239 | Eneli IU, Tylka TL, Watowicz RP, Hummel J, Ritter J, Lumeng JC. Targeting Feeding and Eating Behaviors: Development of the Feeding Dynamic Intervention for Caregivers of 2- to 5-Year-Old Children. J Obes. 2015;2015:964249. doi:10.1155/2015/964249.26199741 | Study design; Outcome
240 | Entin A, Kaufman-Shriqui V, Naggan L, Vardi H, Shahar DR. Parental feeding practices in relation to low diet quality and obesity among LSES children. J Am Coll Nutr. 2014;33(4):306–14. doi:10.1080/07315724.2013.874936.24992282 | Study design
241 | Epstein LH, Gordy CC, Raynor HA, Beddome M, Kilanowski CK, Paluch R. Increasing fruit and vegetable intake and decreasing fat and sugar intake in families at risk for childhood obesity. Obes Res. Mar 2001;9(3):171–8. doi:10.1038/oby.2001.18.11323442 | Intervention/exposure; Outcome
242 | Epstein LH, Kilanowski C, Paluch RA, Raynor H, Daniel TO. Reducing variety enhances effectiveness of family-based treatment for pediatric obesity. Eat Behav. Apr 2015;17:140–3. doi:10.1016/j.eatbeh.2015.02.001.25706950 | Intervention/exposure
243 | Epstein LH, Paluch RA, Beecher MD, Roemmich JN. Increasing healthy eating vs. reducing high energy-dense foods to treat pediatric obesity. Obesity (Silver Spring). Feb 2008;16(2):318–26. doi:10.1038/oby.2007.61.18239639 | Intervention/exposure
244 | Epstein LH, Roemmich JN, Stein RI, Paluch RA, Kilanowski CK. The challenge of identifying behavioral alternatives to food: clinic and field studies. Ann Behav Med. Dec 2005;30(3):201–9. doi:10.1207/s15324796abm3003_4.16336071 | Intervention/exposure
245 | Escobar RS, O'Donnell KA, Colalillo S, Better quality of mother-child interaction at 4 years of age decreases emotional overeating in IUGR girls. Appetite. Oct 2014;81:337–42. doi:10.1016/j.appet.2014.06.107.25014742 | Intervention/exposure; Outcome
246 | Esfarjani F, Khalafi M, Mohammadi F, Family-based intervention for childhood obesity: an experience among tehranian children. Journal article; Conference proceeding. Annals of nutrition & metabolism. 2013;63:844. | Publication status
247 | Essery EV, DiMarco NM, Rich SS, Nichols DL. Mothers of preschoolers report using less pressure in child feeding situations following a newsletter intervention. Journal of Nutrition Education & Behavior. 2008;40(2):110–115.18314087 | Outcome
248 | Estabrooks PA, Shoup JA, Gattshall M, Dandamudi P, Shetterly S, Xu S. Automated telephone counseling for parents of overweight children: a randomized controlled trial. Am J Prev Med. Jan 2009;36(1):35–42. doi:10.1016/j.amepre.2008.09.024.19095163 | Intervention/exposure
249 | EunSeok C, Besse JL. Low parent health literacy is associated with 'obesogenic' infant care behaviours. Evidence Based Nursing. 2015;18(2):46–46.25079221 | Publication status
250 | Evans WD, Christoffel KK, Necheles J, Becker AB, Snider J. Outcomes of the 5–4-3–2-1 Go! Childhood obesity community trial. Am J Health Behav. Mar-Apr 2011;35(2):189–98. doi:10.5993/ajhb.35.2.6.21204681 | Intervention/exposure
251 | Ezendam NP, Evans AE, Stigler MH, Brug J, Oenema A. Cognitive and home environmental predictors of change in sugar-sweetened beverage consumption among adolescents. Br J Nutr. Mar 2010;103(5):768–74. doi:10.1017/s0007114509992297.20003610 | Outcome
252 | Faith MS, Berkowitz RI, Stallings VA, Kerns J, Storey M, Stunkard AJ. Eating in the absence of hunger: a genetic marker for childhood obesity in prepubertal boys? Obesity (Silver Spring). Jan 2006;14(1):131–8. doi:10.1038/oby.2006.16.16493131 | Outcome
253 | Faith MS, Dennison BA, Edmunds LS, Stratton HH. Fruit juice intake predicts increased adiposity gain in children from low-income families: weight status-by-environment interaction. Pediatrics. Nov 2006;118(5):2066–75. doi:10.1542/peds.2006-1117.17079580 | Study design
254 | Fangupo LJ, Heath AL, Williams SM, Impact of an early-life intervention on the nutrition behaviors of 2-y-old children: a randomized controlled trial. Am J Clin Nutr. Sep 2015;102(3):704–12. doi:10.3945/ajcn.115.111823.26224299 | Intervention/exposure; Outcome
255 | Farrow C, Blissett J. Does maternal control during feeding moderate early infant weight gain?. Pediatrics. 2006;118(2):e293–e298. doi:10.1542/peds.2005-2919 16882774 | Age of all participants at intervention/exposure
256 | Farrow, C, Blissett, J, Haycraft, E. Does child weight influence how mothers report their feeding practices?. Int J Pediatr Obes. 2011. 6:306–13 . doi:10.3109/17477166.2011.575160.21728778 | Study design
257 | Farrow C, Blissett J. Stability and continuity of parentally reported child eating behaviours and feeding practices from 2 to 5 years of age. Appetite. Feb 2012;58(1):151–6. doi:10.1016/j.appet.2011.09.005.21986188 | Intervention/exposure; Outcome
258 | Farrow CV, Blissett J. Controlling feeding practices: cause or consequence of early child weight? Pediatrics. Jan 2008;121(1):e164–9. doi:10.1542/peds.2006-3437.18166535 | Age of all participants at intervention/exposure
259 | Farrow CV, Galloway AT, Fraser K. Sibling eating behaviours and differential child feeding practices reported by parents. Appetite. Apr 2009;52(2):307–12. doi:10.1016/j.appet.2008.10.009.19056439 | Study design
260 | Farrow CV, Haycraft E, Blissett JM. Teaching our children when to eat: how parental feeding practices inform the development of emotional eating--a longitudinal experimental design. Am J Clin Nutr. May 2015;101(5):908–13. doi:10.3945/ajcn.114.103713.25787999 | Outcome
261 | Faught E, Vander Ploeg K, Chu YL, Storey K, Veugelers PJ. The influence of parental encouragement and caring about healthy eating on children's diet quality and body weights. Public Health Nutr. Apr 2016;19(5):822–9. doi:10.1017/s1368980015002049.26100617 | Study design
262 | Feeley AB, Musenge E, Pettifor JM, Norris SA. Investigation into longitudinal dietary behaviours and household socio-economic indicators and their association with BMI Z-score and fat mass in South African adolescents: the Birth to Twenty (Bt20) cohort. Public Health Nutr. Apr 2013;16(4):693–703. doi:10.1017/s1368980012003308.22801035 | Intervention/exposure
263 | Fernandez MA, Kubow S, Gray-Donald K, Knight J, Gaskin PS. Drastic increases in overweight and obesity from 1981 to 2010 and related risk factors: results from the Barbados Children's Health and Nutrition Study. Public Health Nutr. Dec 2015;18(17):3070–7. doi:10.1017/s1368980015002190.26228380 | Study design
264 | Fiese BH, Hammons A, Grigsby-Toussaint D. Family mealtimes: a contextual approach to understanding childhood obesity. Econ Hum Biol. 2012;10(4):365–374. doi:10.1016/j.ehb.2012.04.004 22652025 | Study design; Health status
265 | Fiks AG, Gruver RS, Bishop-Gilyard CT, A Social Media Peer Group for Mothers To Prevent Obesity from Infancy: The Grow2Gether Randomized Trial. Child Obes. Oct 2017;13(5):356–368. doi:10.1089/chi.2017.0042.28557558 | Intervention/exposure; Outcome
266 | Fildes A, van Jaarsveld CH, Llewellyn CH, Fisher A, Cooke L, Wardle J. Nature and nurture in children's food preferences. Am J Clin Nutr. Apr 2014;99(4):911–7. doi:10.3945/ajcn.113.077867.24477038 | Study design; Intervention/exposure; Outcome
267 | Fisher JO, Birch LL, Smiciklas-Wright H, Picciano MF. Breast-feeding through the first year predicts maternal control in feeding and subsequent toddler energy intakes. J Am Diet Assoc. Jun 2000;100(6):641–6. doi:10.1016/s0002-8223(00)00190-5.10863566 | Intervention/exposure; Outcome
268 | Fisher JO, Birch LL. Eating in the absence of hunger and overweight in girls from 5 to 7 y of age. Am J Clin Nutr. Jul 2002;76(1):226–31. doi:10.1093/ajcn/76.1.226.12081839 | Intervention/exposure
269 | Fisher JO, Birch LL. Parents' restrictive feeding practices are associated with young girls' negative self-evaluation of eating. J Am Diet Assoc. Nov 2000;100(11):1341–6. doi:10.1016/s0002-8223(00)00378-3.11103656 | Study design
270 | Fisher JO, Liu Y, Birch LL, Rolls BJ. Effects of portion size and energy density on young children's intake at a meal. Am J Clin Nutr. Jul 2007;86(1):174–9. doi:10.1093/ajcn/86.1.174.17616778 | Intervention/exposure; Outcome
271 | Fisher JO, Serrano EL, Foster GD, Efficacy of a food parenting intervention for mothers with low income to reduce preschooler's solid fat and added sugar intakes: a randomized controlled trial. Int J Behav Nutr Phys Act. Jan 17 2019; 16(1):6. doi: 10.1186/s12966-018-0764-3.30654818 | Intervention/exposure
272 | Fisk CM, Crazier SR, Inskip FIM, Godfrey KM, Cooper C, Robinson SM. Influences on the quality of young children's diets: the importance of maternal food choices. Br J Nutr. Jan 2011;105(2):287–96. doi:10.1017/s0007114510003302.20807465 | Study design; Intervention/exposure
273 | Fitzsimons E, Pongiglione B. The impact of maternal employment on children's weight: Evidence from the UK. SSM Popul Health. Apr 2019;7:100333. doi:10.1016/j.ssmph.2018.100333.30581966 | Intervention/exposure
274 | Flieh SM, Miguel-Berges ML, Huybrechts I, Associations between food portion sizes, insulin resistance, V02 max and metabolic syndrome in European adolescents: The HELENA study. Article. Nutrition, Metabolism and Cardiovascular Diseases. 2022;32(9):2061–2073.. doi:10.1016/j.numecd.2022.05.017. | Study design; Intervention/exposure
275 | Flores-Pena Y, He M, Sosa ET, Avila-Alpirez H, Trejo-Ortiz PM, Gutierrez-Sanchez G. Impacts of an early childhood obesity prevention program in Mexico. Health Educ Res. 2022;37(4):242 253. doi:10.1093/her/cyac013 35686999 | Intervention/exposure; Outcome
276 | Flores-Pena Y, Ortiz-Felix RE, Cardenas-Villarreal VM, Avila-Alpirez H, Alba-Alba CM, Hernandez-Carranco RG. Maternal Eating and Physical Activity Strategies and their Relation with Children's Nutritional Status. Rev Lat Am Enfermagem. 2014;22(2):286–292. doi:10.1590/0104-1169.3415.2414 26107837 | Study design
277 | Follansbee-Junger K, Janicke DM, Sallinen BJ. The influence of a behavioral weight management program on disordered eating attitudes and behaviors in children with overweight. J Am Diet Assoc. Nov 2010; 110(11):1653–9. doi:10.1016/j.jada.2010.08.005.21034878 | Intervention/exposure; Outcome
278 | Folta SC, Kuder JF, Goldberg JP, Changes in diet and physical activity resulting from the Shape Up Somerville community intervention. BMC Pediatr. Oct 4 2013;13:157. doi:10.1186/1471-2431-13-157.24093936 | Intervention/exposure; Outcome
279 | Foster BA, Aquino C, Gil M, Flores G, Hale D. A randomized clinical trial of the effects of parent mentors on early childhood obesity: Study design and baseline data. Contemp Clin Trials. Nov 2015;45(Pt B):164–169. doi:10.1016/j.cct.2015.08.017.26343746 | Study design; Intervention/exposure
280 | Foster BA, Aquino CA, Mejia S, Turner BJ, Singhal A. Identification and Characterization of Families That Are Positively Deviant for Childhood Obesity in a Latino Population: A CaseControl Study. J Obes. 2018;2018:9285164. doi:10.1155/2018/9285164.30018820 | Study design
281 | Fowler LA, Litt MD, Rotman SA, Relation of social network support to child health behaviors among children in treatment for overweight/obesity. Article. Eating and Weight Disorders. 2022;27(5): 1669–1678. doi:10.1007/s40519-021-01303-4.34549372 | Intervention/exposure; Outcome
282 | Francis LA, Birch LL. Does eating during television viewing affect preschool children's intake? Journal article. Journal of the American Dietetic Association. 2006;106(4):598–600. doi:10.1016/j.jada.2006.01.008.16567158 | Outcome
283 | Francis LA, Hofer SM, Birch LL. Predictors of maternal child-feeding style: maternal and child characteristics. Appetite. Dec 2001;37(3):231–43. doi:10.1006/appe.2001.0427.11895324 | Study design
284 | Francis LA, Nix RL, BeLue R, Designing a childhood obesity preventive intervention using the multiphase optimization strategy: The Healthy Bodies Project. Clin Trials. Aug 2023;20(4):434–446. doi:10.1177/17407745231167115.37077032 | Outcome
285 | Frankel LA, O'Connor TM, Chen TA, Nicklas T, Power TG, Hughes SO. Parents' perceptions of preschool children's ability to regulate eating. Feeding style differences. Appetite. May 2014;76:166–74. doi:10.1016/j.appet.2014.01.077.24533968 | Study design
286 | Frate N, Jenull B, Birnbacher R. Like father, like son. Physical Activity, Dietary Intake, and Media Consumption in Pre-School-Aged Children. Int J Environ Res Public Health. Jan 23 2019; 16(3) doi:10.3390/ijerph16030306. | Study design
287 | Freeh A. Healthy Behavior Trajectories between Adolescence and Young Adulthood. Adv Life Course Res. Jun 1 2012;17(2):59–68. doi:10.1016/j.alcr.2012.01.003.22745923 | Intervention/exposure; Outcome
288 | French SA, Sherwood NE, Veblen-Mortenson S, Multicomponent Obesity Prevention Intervention in Low-Income Preschoolers: primary and Subgroup Analyses of the NET-Works Randomized Clinical Trial, 2012–2017. Journal Article; Clinical Trial Protocol. American journal of public health. 2018;108(12):1695–1706. doi:10.2105/AJPH.2018.304696.30403521 | Intervention/exposure
289 | Frenn M, Heinrich A, Dohmen CS, Pruszynski JE. What can parents do to reduce youth obesity? An initial study with a diverse sample. J Pediatr Nurs. Oct 2011;26(5):428–34. doi:10.1016/j.pedn.2010.09.001.21930029 | Study design
290 | Frenn M, Pruszynski JE, Felzer H, Zhang J. Authoritative feeding behaviors to reduce child BMI through online interventions. J Spec Pediatr Nurs. Jan 2013;18(1):65–77. doi:10.1111/jspn.12008.23289456 | Age of all participants at intervention/exposure
291 | Fu E, Grimm KJ, Berkel C, Smith JD. Parenting and social-ecological correlates with children's health behaviours: A latent profile analysis. Pediatric Obesity. 2020; 15(10):1–11. doi:10.1111/ijpo.12721. | Study design; Outcome
292 | Fuemmeler BF, Stroo M, Lee CT, Bazemore S, Blocker B, Ostbye T. Racial Differences in Obesity-Related Risk Factors Between 2-Year-Old Children Born of Overweight Mothers. J Pediatr Psychol. Aug 2015;40(7):649–56. doi:10.1093/jpepsy/jsv023.25797946 | Study design; Intervention/exposure
293 | Fuglestad AJ, Demerath EW, Finsaas MC, Moore CJ, Georgieff MK, Carlson SM. Maternal executive function, infant feeding responsiveness and infant growth during the first 3 months. Pediatr Obes. 2017;12 Suppl 1:102–110. doi:10.1111/ijpo.12226 | Age of all participants at intervention/exposure
294 | Fulkerson J, Barr-Anderson D, Florning M, Flome food environment and child dietary and physical activity outcomes of the nu-home RCT. Journal article; Conference proceeding. Obesity (Silver Spring, Md). 2021;29(SUPPL 2):112. | Publication status
295 | Fulkerson JA, Farbakhsh K, Lytle L, Away-from-home family dinner sources and associations with weight status, body composition, and related biomarkers of chronic disease among adolescents and their parents. J Am Diet Assoc. Dec 2011;111(12): 1892–7. doi:10.1016/j.jada.2011.09.035.22117665 | Study design
296 | Fulkerson JA, Friend S, Flattum C, Promoting healthful family meals to prevent obesity: FIOME Plus, a randomized controlled trial. Int J Behav Nutr Phys Act. Dec 15 2015;12:154. doi:10.1186/s12966-015-0320-3.26667110 | Intervention/exposure
297 | Fulkerson JA, Friend S, Horning M, Family Home Food Environment and Nutrition-Related Parent and Child Personal and Behavioral Outcomes of the Healthy Home Offerings via the Mealtime Environment (HOME) Plus Program: A Randomized Controlled Trial. J Acad Nutr Diet. Feb 2018;118(2):240–251. doi:10.1016/j.jand.2017.04.006.28578900 | Intervention/exposure; Outcome
298 | Fulkerson JA, Kubik MY, Story M, Lytle L, Arcan C. Are there nutritional and other benefits associated with family meals among at-risk youth? J Adolesc Health. Oct 2009;45(4):389–95. doi:10.1016/j.jadohealth.2009.02.011.19766944 | Study design
299 | Fulkerson JA, Neumark-Sztainer D, Hannan PJ, Story M. Family meal frequency and weight status among adolescents: cross-sectional and 5-year longitudinal associations. Obesity (Silver Spring). Nov 2008;16(11):2529–34. doi:10.1038/oby.2008.388.18719674 | Age of all participants at intervention/exposure
300 | Fulkerson JA, Rydell S, Kubik MY, Healthy Home Offerings via the Mealtime Environment (HOME): feasibility, acceptability, and outcomes of a pilot study. Obesity (Silver Spring). Feb 2010;18 Suppl 1(Suppl 1):S69–74. doi:10.1038/oby.2009.434.20107464 | Age of all participants at intervention/exposure
301 | Fulkerson JA, Story M, Mellin A, Leffert N, Neumark-Sztainer D, French SA. Family dinner meal frequency and adolescent development: relationships with developmental assets and high-risk behaviors. J Adolesc Health. Sep 2006;39(3):337–45. doi:10.1016/j.jadohealth.2005.12.026.16919794 | Study design
302 | Gable S, Lutz S. Nutrition socialization experiences of children in the Head Start program. J Am Diet Assoc. May 2001;101(5):572–7. doi:10.1016/s0002-8223(01)00143-2.11374352 | Study design
303 | Gaffney KF, Brito AV, Kitsantas P, Kermer DA. Early Feeding Practices and Weight Status at One Year of Age: A Comparison of Hispanic Immigrant Mother-Infant Dyads with Participants of the Infant Feeding Practices Study II. Child Obes. Oct 2016; 12(5):384–91. doi:10.1089/chi.2016.0037.27385467 | Intervention/exposure
304 | Gago C, Beckerman-Hsu J, Figueroa R, Increased empowerment is associated with healthier obesity-related parenting practices overtime. Journal article; Conference proceeding. Obesity (Silver Spring, Md). 2020;28(SUPPL 2):113. | Publication status
305 | Gago C, Aftosmes-Tobio A, Beckerman-Hsu JP, Evaluation of a cluster-randomized controlled trial: Communities for Healthy Living, family-centered obesity prevention program for Head Start parents and children. Int J Behav Nutr Phys Act. Jan 11 2023;20(1 ):4. doi:10.1186/s12966-022-01400-2.36803988 | Intervention/exposure; Outcome
306 | Galindo L, Power TG, Beck AD, Fisher JO, O'Connor TM, Hughes SO. Predicting preschool children's eating in the absence of hunger from maternal pressure to eat: A longitudinal study of low-income, Latina mothers. Appetite. Jan 1 2018;120:281–286. doi:10.1016/j.appet.2017.09.007.28899652 | Outcome
307 | Galloway AT, Farrow CV, Martz DM. Retrospective reports of child feeding practices, current eating behaviors, and BMI in college students. Obesity (Silver Spring). Jul 2010; 18(7): 1330–5. doi:10.1038/oby.2009.393.19876005 | Study design
308 | Galloway AT, Watson P, Pitama S, Farrow CV. Socioeconomic Position and Picky Eating Behavior Predict Disparate Weight Trajectories in Infancy. Front Endocrinol (Lausanne). 2018;9:528. doi:10.3389/fendo.2018.00528.30279678 | Intervention/exposure
309 | Gattshall ML, Shoup JA, Marshall JA, Crane LA, Estabrooks PA. Validation of a survey instrument to assess home environments for physical activity and healthy eating in overweight children. Int J Behav Nutr Phys Act. Jan 11 2008;5:3. doi:10.1186/1479-5868-5-3.18190709 | Study design; Outcome
310 | Gemmill AW, Worotniuk T, Holt CJ, Skouteris H, Milgrom J. Maternal psychological factors and controlled child feeding practices in relation to child body mass index. Child Obes. Aug 2013;9(4):326–37. doi:10.1089/chi.2012.0135.23782306 | Study design
311 | Gerards SM, Dagnelie PC, Gubbels JS, The effectiveness of lifestyle triple P in the Netherlands: a randomized controlled trial. PLoS One. 2015;10(4):e0122240. doi:10.1371/journal.pone.0122240.25849523 | Intervention/exposure
312 | Gevers DW, Kremers SP, e Vries NK, van Assema P. Intake of energy-dense snack foods and drinks among Dutch children aged 7–12 years: how many, how much, when, where and which? Public Health Nutr. Jan 2016;19(1):83–92. doi:10.1017/s1368980015000877.25850560 | Study design; Intervention/exposure
313 | Gevers DW, van Assema P, Sleddens EF, e Vries NK, Kremers SP. Associations between general parenting, restrictive snacking rules, and adolescent's snack intake. The roles of fathers and mothers and interparental congruence. Appetite. Apr 2015;87:184–91. doi:10.1016/j.appet.2014.12.220.25555538 | Study design
314 | Ghofranipour F, Hamzavi Zarghani N, Mohammadi E, An internet-based educational intervention for mothers targeting preschoolers' weight management promotion (PWMP): a pilot study. BMC Public Health. Nov 29 2022;22(1):2220. doi:10.1186/s12889-022-14543-5.36447163 | Study design; Intervention/exposure
315 | Gholami M, Wiedemann A, Knoll N, Schwarzer R. Mothers improve their daughters' vegetable intake: a randomized controlled trial. Psychol Health Med. 2015;20(1):1–7. doi:10.1080/13548506.2014.902485.24689952 | Outcome
316 | Gibbs BG, Forste R. Socioeconomic status, infant feeding practices and early childhood obesity. Pediatr Obes. Apr 2014;9(2):135–46. doi:10.1111/j.2047-6310.2013.00155.x.23554385 | Intervention/exposure
317 | Gillis D, Brauner M, Granot E. A community-based behavior modification intervention for childhood obesity. J Pediatr Endocrinol Metab. Feb 2007;20(2):197–203. doi:10.1515/jpem.2007.20.2.197.17396436 | Intervention/exposure
318 | Gipson-Jones TL, O'Neal LJ, Sheats JL, Food Security Status and Overweight/Obesity Among 2- to 5-Year-Old Boys and Girls in a Community-Based Clinic. Family & Community Health. 2019;42(2):117–122. doi:10.1097/FCH.0000000000000218.30768476 | Study design; Intervention/exposure
319 | Goldfield GS, Murray MA, Buchholz A, Family meals and body mass index among adolescents: effects of gender. Appl Physiol Nutr Metab. Aug 2011;36(4):539–46. doi:10.1139/h11-049.21851205 | Study design
320 | Goldfield GS, Paluch R, Keniray K, Hadjiyannakis S, Lumb AB, Adamo K. Effects of breastfeeding on weight changes in family-based pediatric obesity treatment. J Dev Behav Pediatr. Apr 2006;27(2):93–7. doi:10.1097/00004703-200604000-00002.16682871 | Intervention/exposure
321 | Goldstein, GL, Daun, H, Tepper, BJ. Influence of PROP taster status and maternal Goldstein GL, Daun H, Tepper BJ. Influence of PROP taster status and maternal variables on energy intake and body weight of pre-adolescents. Physiol Behav. Apr 23 2007;90(5):809–17. doi:10.1016/j.physbeh.2007.01.004.17313965 | Study design
322 | Goldstein T, Serok E, Kark JD. Joint parent-children nutritional activities may improve BMI in children who are overweight or obese. Journal article; Conference proceeding. Annals of nutrition & metabolism. 2015;67:427. | Publication status
323 | Gonçalves S, Silva M, Gomes AR, Machado PP. Disordered eating among preadolescent boys and girls: the relationship with child and maternal variables. Nutrients. Apr 2012;4(4):273–85. doi:10.3390/nu4040273.22606370 | Study design; Intervention/exposure
324 | González ODJ, Tugault-Lafleur CN, Buckler EJ, The Aim2Be mHealth Intervention for Children with Overweight or Obesity and Their Parents: Person-Centered Analyses to Uncover Digital Phenotypes. Article. Journal of Medical Internet Research. 2022;24(6) doi:10.2196/35285. | Intervention/exposure
325 | Goossens L, Braet C, Van Durme K, Decaluwé V, Bosmans G. The parent-child relationship as predictor of eating pathology and weight gain in preadolescents. J Clin Child Adolesc Psychol. 2012;41(4):445–57. doi:10.1080/15374416.2012.660690.22432541 | Intervention/exposure
326 | Gordon-Larsen P, Harris KM, Ward DS, Popkin BM. Acculturation and overweight-related behaviors among Hispanic immigrants to the US: the National Longitudinal Study of Adolescent Health. Soc Sci Med. Dec 2003;57(11):2023–34. doi:10.1016/s0277-9536(03)00072-8.14512234 | Intervention/exposure
327 | Gouveia MJ, Canavarro MC, Moreira H. The role of mindful parenting and children's weight in mothers' child-feeding practices. Eat Weight Disord. Apr 2020;25(2):427–435. doi:10.1007/s40519-018-0615-x.30430466 | Study design; Intervention/exposure
328 | Goyal RK, Shah VN, Saboo BD, Prevalence of overweight and obesity in Indian adolescent school going children: its relationship with socioeconomic status and associated lifestyle factors. J Assoc Physicians India. 2010;58:151–158.20848812 | Intervention/exposure; Country
329 | Goyena EA, Valdeabella Maniego ML. Adherence to age-appropriate feeding practices among Filipino children under two: An analysis of the 2018–2019 Expanded National Nutrition Survey. Malaysian Journal of Nutrition. 2022;28(3):423–439. doi:10.31246/mjn-2022-0037. | Intervention/exposure
330 | Grammer AC, Best JR, Fowler LA, Change in parent and child psychopathology following obesity treatment and maintenance: A secondary data analysis. Pediatr Obes. Jan 2023;18(1):e12971. doi:10.1111/ijpo.12971.35971859 | Intervention/exposure
331 | Grassi E, Evans A, Ranjit N, Pria SD, Messina L. Using a mixed-methods approach to measure impact of a school-based nutrition and media education intervention study on fruit and vegetable intake of Italian children. Public Health Nutr. Aug 2016;19(11):1952–63. doi:10.1017/s1368980015003729.26857624 | Intervention/exposure
332 | Gray LA, Hernandez Alava M, Kelly MP, Campbell MJ. Family lifestyle dynamics and childhood obesity: evidence from the millennium cohort study. BMC Public Health. Apr 16 2018;18(1):500. doi:10.1186/s12889-018-5398-5.29807535 | Intervention/exposure
333 | Gray WN, Janicke DM, Wistedt KM, Dumont-Driscoll MC. Factors associated with parental use of restrictive feeding practices to control their children's food intake. Appetite. Oct 2010;55(2):332–7.. doi:10.1016/j.appet.2010.07.005.20633586 | Study design
334 | Gregory JE, Paxton SJ, Brozovic AM. Maternal feeding practices predict fruit and vegetable consumption in young children. Results of a 12-month longitudinal study. Appetite. Aug 2011;57(1):167–72. doi:10.1016/j.appet.2011.04.012.21569809 | Age of all participants at intervention/exposure
335 | Gregory JE, Paxton SJ, Brozovic AM. Pressure to eat and restriction are associated with child eating behaviours and maternal concern about child weight, but not child body mass index, in 2-to 4-year-old children. Appetite. Jun 2010;54(3):550–6. doi:10.1016/j.appet.2010.02.013.20219609 | Study design
336 | Griauzde DH, Lumeng JC, Shah PE, Kaciroti N. Lower Body Mass Index Z-Score Trajectory During Early Childhood After the Birth of a Younger Sibling. Acad Pediatr. Jan-Feb 2019;19(1):51–57. doi:10.1016/j.acap.2018.06.003.29920332 | Intervention/exposure
337 | Gross RS, Briggs RD, Hershberg RS, Early Child Social-Emotional Problems and Child Obesity: Exploring the Protective Role of a Primary Care-Based General Parenting Intervention. J Dev Behav Pediatr. Oct 2015;36(8):594–604. doi:10.1097/dbp.0000000000000212.26375801 | Study design; Intervention/exposure; Outcome
338 | Grummer-Strawn LM, Ruowei L, Perrine CG, Scanlon KS, Fein SB. Infant Feeding and Long-Term Outcomes: Results From the Year 6 Follow-Up of Children in the Infant Feeding Practices Study II. Pediatrics. 2014;134:S1–3.25183749 | Study design
339 | Gubbels JS, Kremers SP, Goldbohm RA, Stafleu A, Thijs C. Energy balance-related behavioural patterns in 5-year-old children and the longitudinal association with weight status development in early childhood. Public Health Nutr. Aug 2012;15(8):1402–10. doi:10.1017/s1368980011003089.22124196 | Intervention/exposure
340 | Gubbels JS, Kremers SP, Stafleu A, Diet-related restrictive parenting practices. Impact on dietary intake of 2-year-old children and interactions with child characteristics. Appetite. Apr 2009;52(2):423–9. doi:10.1016/j.appet.2008.12.002.19114065 | Study design; Outcome
341 | Guivarch C, Charles MA, Forhan A, Ong KK, Heude B, e Lauzon-Guillain B. Associations between Children's Genetic Susceptibility to Obesity, Infant's Appetite and Parental Feeding Practices in Toddlerhood. Nutrients. Apr 26 2021;13(5). doi:10.3390/nu13051468. | Intervention/exposure; Outcome
342 | Güngör Ş, Büyükavcı MA, Acıpayam C. Effects of parent- and child-related behavioral feeding problems in early childhood on malnutrition. Arch Pediatr. May 2023;30(4):206–211. doi:10.1016/j.arcped.2022.11.018.36925345 | Study design; Health status
343 | Gunther C, Rogers C, Holloman C, Child diet and health outcomes of the simple suppers program: a 10-week, 2-group quasi-experimental family meals trial. Journal article. BMC public health. 2019;19(1):1657. doi:10.1186/s12889-019-7930-7.31823753 | Intervention/exposure
344 | Hacioglu DO, Simsek H. The effect of healthy life approaches applied to families of children in preschool on obesity and healthy life behaviour. Article. Progress in Nutrition. 2019;21(1):34–45. doi:10.23751/pn.v21i1.6141. | Study design; Outcome; Comparator
345 | Hails KA, Whipps MDM, Gross RS, Breastfeeding and Responsive Parenting as Predictors of Infant Weight Change in the First Year. J Pediatr Psychol. 2021;46(7):768–778. doi:10.1093/jpepsy/jsab049 34270767 | Intervention/exposure
346 | Haines J, Douglas S, Mirotta JA, Guelph Family Health Study: pilot study of a home-based obesity prevention intervention. Can J Public Health. Aug 2018;109(4):549–560. doi:10.17269/s41997-018-0072-3.29981086 | Intervention/exposure
347 | Haines J, McDonald J, O'Brien A, Healthy Habits, Happy Homes: randomized trial to improve household routines for obesity prevention among preschool-aged children. JAMA Pediatr. Nov 2013;167(11):1072–9. doi:10.1001/jamapediatrics.2013.2356. | Intervention/exposure
348 | Haines J, Rifas-Shiman SL, Gross D, McDonald J, Kleinman K, Gillman MW. Randomized trial of a prevention intervention that embeds weight-related messages within a general parenting program. Obesity (Silver Spring). Jan 2016;24(1):191–9. doi:10.1002/oby.21314.26638185 | Intervention/exposure
349 | Haire-Joshu D, Elliott MB, Caito NM, High 5 for Kids: the impact of a home visiting program on fruit and vegetable intake of parents and their preschool children. Prev Med. Jul 2008;47(1):77–82. doi:10.1016/j.ypmed.2008.03.016.18486203 | Outcome
350 | Haire-Joshu D, Schwarz C, Jacob R, Raising Well at Home: a pre-post feasibility study of a lifestyle intervention for caregivers and their child with obesity. Pilot Feasibility Stud. 2020;6:149. doi:10.1186/s40814-020-00692-0.33042569 | Study design; Intervention/exposure
351 | Hajna S, Leblanc PJ, Faught BE, Associations between family eating behaviours and body composition measures in peri-adolescents: results from a community-based study of school-aged children. Can J Public Health. Jan 10 2014;105(1):e15–21. 105:e15–21. doi:10.17269/cjph.105.4150.24735691 | Study design
352 | Hales D, Vaughn AE, Mazzucca S, Development of HomeSTEAD's physical activity and screen time physical environment inventory. Int J Behav Nutr Phys Act. Dec 5 2013;10:132. doi:10.1186/1479-5868-10-132.24313962 | Study design; Outcome
353 | Hamilton K, Daniels L, White KM, Murray N, Walsh A. Predicting mothers' decisions to introduce complementary feeding at 6 months. An investigation using an extended theory of planned behaviour. Appetite. 2011;56(3):674–681. doi:10.1016/j.appet.2011.02.002 21316413 | Intervention/exposure; Outcome; Publication status
354 | Hankey M, Williams NA, Dev D. Uninvolved Maternal Feeding Style Moderates the Association of Emotional Overeating to Preschoolers' Body Mass Index z-Scores. J Nutr Educ Behav. Sep 2016;48(8):530–537.e1. doi:10.1016/j.jneb.2016.06.006.27450701 | Study design
355 | Harbec MJ, Pagani LS. Associations Between Early Family Meal Environment Quality and Later Well-Being in School-Age Children. J Dev Behav Pediatr. Feb/Mar 2018;39(2):136–143. doi:10.1097/dbp.0000000000000520.29227338 | Intervention/exposure; Outcome
356 | Hare ME, Coday M, Williams NA, Richey PA, Tylavsky FA, Bush AJ. Methods and baseline characteristics of a randomized trial treating early childhood obesity: the Positive Lifestyles for Active Youngsters (Team PLAY) trial. Contemp Clin Trials. May 2012;33(3):534–49. doi:10.1016/j.cct.2012.02.003.22342450 | Study design
357 | Harris JL, Bargh JA. Television viewing and unhealthy diet: implications for children and media interventions. Health Commun. Oct 2009;24(7):660–73. doi:10.1080/10410230903242267.20183373 | Study design; Intervention/exposure; Outcome
358 | Harrison M, Brodribb W, Davies PSW, Hepworth J. Relationships between parental feeding practices, infant weight concern, infant dietary behaviour and body weight: Findings from the Feeding A Baby (FAB) Study. Obesity Research & Clinical Practice. 2019;13(1):86–86. doi:10.1016/j.orcp.2016.10.238. | Study design; Publication status
359 | Hart CN, Phelan S, Coffman DL, Maternal responsiveness and toddler body mass index z-score: Prospective analysis of maternal and child mealtime interactions. Appetite. 2023;180:106348. doi:10.1016/j.appet.2022.106348 36272545 | Age of all participants at intervention/exposure
360 | Hart LM, Damiano SR, Li-Wai-Suen CSN, Paxton SJ. Confident body, confident child: Evaluation of a universal parenting resource promoting healthy body image and eating patterns in early childhood-6- and 12-month outcomes from a randomized controlled trial. Int J Eat Disord. Feb 2019;52(2):121–131. doi:10.1002/eat.22992.30636006 | Intervention/exposure; Outcome
361 | Harvey H, Coleman G. Raising healthy eaters: a parenting and nutrition curriculum. J Nutr Educ Behav. 2008;40(1):52–53. doi:10.1016/j.jneb.2007.05.001 18174106 | Outcome; Publication status
362 | Harvey-Berino J, Rourke J. Obesity prevention in preschool native-american children: a pilot study using home visiting. Obes Res. May 2003;11(5):606–11. doi:10.1038/oby.2003.87.12740449 | Intervention/exposure
363 | Hasenboehler K, Munsch S, Meyer AH, Kappler C, Vögele C. Family structure, body mass index, and eating behavior. Int J Eat Disord. May 2009;42(4):332–8. doi:10.1002/eat.20612.19107830 | Study design
364 | Hashemi Risi F, Soltani R, Eslami A, Hasanzadeh A. Effects of family based education programs on body mass index of overweight and obese children: an intervention based on the social-cognitive theory. Journal article. Iranian journal of endocrinology and metabolism. 2017;19(3):151–160. | Publication language
365 | Haszard JJ, Russell CG, Byrne RA, Taylor RW, Campbell KJ. Early maternal feeding practices: Associations with overweight later in childhood. Appetite. Jan 1 2019;132:91–96. doi:10.1016/j.appet.2018.10.008.30308224 | Age of all participants at intervention/exposure
366 | Haszard JJ, Skidmore PM, Williams SM, Taylor RW. Associations between parental feeding practices, problem food behaviours and dietary intake in New Zealand overweight children aged 4–8 years. Public Health Nutr. Apr 2015;18(6):1036–43. doi:10.1017/s1368980014001256.24955942 | Study design
367 | Haszard JJ, Williams SM, Dawson AM, Skidmore PM, Taylor RW. Factor analysis of the Comprehensive Feeding Practices Questionnaire in a large sample of children. Appetite. Mar 2013;62:110–8. doi:10.1016/j.appet.2012.11.017.23207187 | Study design; Outcome
368 | Haycraft EL, Blissett JM. Maternal and paternal controlling feeding practices: reliability and relationships with BMI. Obesity (Silver Spring). Jul 2008;16(7):1552–8. doi:10.1038/oby.2008.238.18421263 | Study design
369 | Haycraft E, Blissett J. Predictors of paternal and maternal controlling feeding practices with 2- to 5-year-old children. J Nutr Educ Behav. 2012;44(5):390–397. doi:10.1016/j.jneb.2010.03.001 21371945 | Study design
370 | Hayes JF, Balantekin KN, Conlon RPK, Home and neighbourhood built environment features in family-based treatment for childhood obesity. Journal article. Pediatric obesity. 2019;14(3):e12477. doi:10.1111/ijpo.12477.30378768 | Study design; Intervention/exposure
371 | He Q, Ding ZY, Fong DY, Karlberg J. Risk factors of obesity in preschool children in China: a population-based case--control study. Int J Obes Relat Metab Disord. Nov 2000;24(11):1528–36. doi:10.1038/sj.ijo.0801394.11126352 | Country
372 | He Q, Li X, Wang R. Childhood obesity in China: Does grandparents' coresidence matter? Econ Hum Biol. May 2018;29:56–63. doi:10.1016/j.ehb.2018.02.001.29482154 | Study design; Intervention/exposure
373 | Heerman WJ, Burgess LE, Escarfuller J, Competency Based Approach to Community Health (COACH): The methods of a family-centered, community-based, individually adaptive obesity randomized trial for pre-school child-parent pairs. Contemp Clin Trials. Oct 2018;73:1–7. doi:10.1016/j.cct.2018.08.006.30144630 | Study design; Intervention/exposure
374 | Heird WC. Parental feeding behavior and children's fat mass. Am J Clin Nutr. 2002;75(3):451–452. doi:10.1093/ajcn/75.3.451 11864849 | Publication status
375 | Helle C, Hillesund ER, Wills AK, Overby NC. Examining the effects of an eHealth intervention from infant age 6 to 12 months on child eating behaviors and maternal feeding practices one year after cessation: The Norwegian randomized controlled trial Early Food for Future Health. PLoS One. 2019;14(8):e0220437. doi:10.1371/journal.pone.0220437.31442241 | Intervention/exposure; Comparator
376 | Hendrie GA, Coveney J, Cox DN. Factor analysis shows association between family activity environment and children's health behaviour. Aust N Z J Public Health. Dec 2011;35(6):524–9. doi:10.1111/j.1753-6405.2011.00775.x.22151158 | Study design; Intervention/exposure
377 | Hendy HM, Williams KE, Harclerode W, Riegel K. Parent Attribution for Child Eating Scale (PACES). Psychometric characteristics and associations with child and parent variables. Appetite. Oct 2014;81:312–9. doi:10.1016/j.appet.2008.11.003. | Study design; Outcome
378 | Hendy, HM, Williams, KE, Harclerode, W, Riegel, K. Parent Attribution for Child Eating Scale (PACES). Psychometric characteristics and associations with child and parent variables. Appetite. 2014. 81:312–9. doi:10.1016/j.appet.2014.06.029.24979332 | Study design; Outcome
379 | Hendy HM, Williams KE. Mother's feeding practices for children 3–10 years of age and their associations with child demographics. Appetite. Apr 2012;58(2):710–6. doi:10.1016/j.appet.2012.01.011.22269792 | Study design
380 | Herbenick SK, James K, Milton J, Cannon D. Effects of family nutrition and physical activity screening for obesity risk in school-age children. J Spec Pediatr Nurs. Oct 2018;23(4):e12229. doi:10.1111/jspn.12229.30485639 | Study design; Intervention/exposure
381 | Herle M, Pickles A, Micali N, Abdulkadir M, De Stavola BL. Parental feeding and childhood genetic risk for obesity: exploring hypothetical interventions with causal inference methods. Int J Obes (Lond). Jul 2022;46(7):1271–1279. doi:10.1038/s41366-022-01106-2.35306528 | Age of all participants at intervention/exposure
382 | Herr RM, De Bock F, Diehl K, Associations of individual factors and early childhood education and care (ECEC) centres characteristics with preschoolers' BMI in Germany. Article. BMC public health. 2022;22(1):1415. doi:10.1186/s12889-022-13814-5.35883054 | Study design; Intervention/exposure
383 | Hesketh KD, Salmon J, McNaughton SA, Long-term outcomes (2 and 3.5 years postintervention) of the INFANT early childhood intervention to improve health behaviors and reduce obesity: cluster randomised controlled trial follow-up. Int J Behav Nutr Phys Act. Jul 25 2020;17(1):95. doi:10.1186/s12966-020-00994-9.32711523 | Intervention/exposure
384 | Hester M. Impact of picky eating in early childhood. Contemporary Pediatrics. 2020;37(8):27–27. | Outcome; Publication status
385 | Hirschler V, Gonzalez C, Talgham S, Jadzinsky M. Do mothers of overweight Argentinean preschool children perceive them as such? Pediatr Diabetes. Aug 2006;7(4):201–4. doi:10.1111/j.1399-5448.2006.00183.x.16911006 | Study design
386 | Hittner JB, Johnson C, Tripicchio G, Faith MS. Infant emotional distress, maternal restriction at a home meal, and child BMI gain through age 6years in the Colorado Adoption Project. Eat Behav. Apr 2016;21:135–41. doi:10.1016/j.eatbeh.2016.01.008.26872074 | Age of all participants at intervention/exposure
387 | Hodges EA, Houck GM, Kindermann T. Reliability of the Nursing Child Assessment Feeding Scale during toddlerhood. Issues Compr Pediatr Nurs. Jul-Sep 2007;30(3):109–30. doi:10.1080/01460860701525204.17885829 | Outcome
388 | Hoerr SL, Hughes SO, Fisher JO, Nicklas TA, Liu Y, Shewchuk RM. Associations among parental feeding styles and children's food intake in families with limited incomes. Int J Behav Nutr Phys Act. Aug 13 2009;6:55. doi:10.1186/1479-5868-6-55.19678947 | Study design
389 | Hoffhines H, Whaley KD, Blackett PR, Early childhood nutrition in an American Indian community: educational strategy for obesity prevention. J Okla State Med Assoc. Feb 2014;107(2):55–9.24761552 | Intervention/exposure
390 | Hohman EE, Savage JS, Stansfield BK, Lavner JA. Sleep SAAF Responsive Parenting Intervention for Black Mothers Impacts Response to Infant Crying: A Randomized Clinical Trial. Acad Pediatr. May 5 2023. doi:10.1016/j.acap.2023.04.012. | Outcome
391 | Holdsworth EA, Schell LM. Maternal-infant interaction as an influence on infant adiposity. Am J Hum Biol. Sep 10 2017;29(5). doi:10.1002/ajhb.23023. | Study design; Intervention/exposure
392 | Holland JC, Kolko RP, Stein RI, Modifications in parent feeding practices and child diet during family-based behavioral treatment improve child zBMI. Obesity (Silver Spring). May 2014;22(5):E119–26 doi:10.1002/oby.20708.24458836 | Age of all participants at intervention/exposure
393 | Hollén LI, Din Z, Jones LR, Emond AM, Emmett P. Are diet and feeding behaviours associated with the onset of and recovery from slow weight gain in early infancy? Br J Nutr. May 2014;111(9):1696–704. doi:10.1017/s0007114513004182.24502920 | Intervention/exposure
394 | Hood MY, Moore LL, Sundarajan-Ramamurti A, Singer M, Cupples LA, Ellison RC. Parental eating attitudes and the development of obesity in children. The Framingham Children's Study. Int J Obes Relat Metab Disord. Oct 2000;24(10):1319–25. doi:10.1038/sj.ijo.0801396.11093294 | Intervention/exposure
395 | Hootman KC, Guertin KA, Cassano PA. Stress and psychological constructs related to eating behavior are associated with anthropometry and body composition in young adults. Appetite. Jun 1 2018;125:287–294. doi:10.1016/j.appet.2018.01.003.29309851 | Intervention/exposure; Age of all participants at intervention/exposure
396 | Hop LT, Gross R, Giay T, Sastroamidjojo S, Schultink W, Lang NT. Premature complementary feeding is associated with poorer growth of vietnamese children. J Nutr. Nov 2000;130(11):2683–90. doi:10.1093/jn/130.11.2683.11053507 | Intervention/exposure
397 | Horning ML, Fulkerson JA, Friend SE, Neumark-Sztainer D. Associations among Nine Family Dinner Frequency Measures and Child Weight, Dietary, and Psychosocial Outcomes. J Acad Nutr Diet. Jun 2016;116(6):991–9. doi:10.1016/j.jand.2015.12.018.26875023 | Study design
398 | Horodynski MA, Hoerr S, Coleman G. Nutrition education aimed at toddlers: a pilot program for rural, low-income families. Fam Community Health. Apr-Jun 2004;27(2):103–13. doi:10.1097/00003727-200404000-00003.15596977 | Outcome
399 | Horodynski MA, Stommel M. Nutrition education aimed at toddlers: an intervention study. Pediatr Nurs. Sep-Oct 2005;31(5):364, 367-72.16295151 | Outcome
400 | Hsiao-Liang P, Contento IR, Lee H. Relationship of Chinese American Parental Perceptions, Feeding Practices, Styles and Level of Acculturation to Their Child's BMI. Journal of Nutrition Education & Behavior. 2013;45(4 Supplement):S58–S58. | Study design; Publication status
401 | Huang CY, Reisch LA, Gwozdz W, Pester power and its consequences: do European children's food purchasing requests relate to diet and weight outcomes? Public Health Nutr. Sep 2016;19(13):2393–403. doi:10.1017/s136898001600135x.27297518 | Intervention/exposure
402 | Huang SH, Parks EP, Kumanyika SK, Child-feeding practices among Chinese-American and non-Hispanic white caregivers. Appetite. Jun 2012;58(3):922–7. doi:10.1016/j.appet.2012.02.008.22343192 | Study design
403 | Hubbs-Tait L, Dickin KL, Sigman-Grant M, Jahns L, Mobley AR. Relation of parenting styles, feeding styles and feeding practices to child overweight and obesity. Direct and moderated effects [retracted in: Appetite. 2013 Dec;71:R1. doi: 10.1016/j.appet.2013.11.007]. Appetite. 2013;71:126–136. doi:10.1016/j.appet.2013.08.004 23962403 | Publication status; Retracted
404 | Hughes AR, Stewart L, Chapple J, Randomized, controlled trial of a best-practice individualized behavioral program for treatment of childhood overweight: Scottish Childhood Overweight Treatment Trial (SCOTT). Pediatrics. Mar 2008;121(3):e539–46. doi:10.1542/peds.2007-1786.18310175 | Intervention/exposure
405 | Hughes SO, Anderson CB, Power TG, Micheli N, Jaramillo S, Nicklas TA. Measuring feeding in low-income African-American and Hispanic parents. Appetite. Mar 2006;46(2):215–23. doi:10.1016/j.appet.2006.01.002.16504340 | Study design
406 | Hughes SO, Power TG, Beck A, Short-Term Effects of an Obesity Prevention Program Among Low-Income Hispanic Families With Preschoolers. J Nutr Educ Behav. Mar 2020;52(3):224–239. doi:10.1016/j.jneb.2019.12.001.31917129 | Intervention/exposure; Outcome
407 | Hughes SO, Power TG, Beck AD, Twelve-Month Efficacy of an Obesity Prevention Program Targeting Hispanic Families With Preschoolers From Low-Income Backgrounds. J Nutr Educ Behav. Aug 2021;53(8):677–690. doi:10.1016/j.jneb.2021.04.460.34148764 | Intervention/exposure
408 | Hughes SO, Power TG, Papaioannou MA, Emotional climate, feeding practices, and feeding styles: an observational analysis of the dinner meal in Head Start families. Int J Behav Nutr Phys Act. Jun 10 2011;8:60. doi:10.1186/1479-5868-8-60.21663653 | Study design
409 | Hughes SO, Shewchuk RM, Baskin ML, Nicklas TA, Qu H. Indulgent feeding style and children's weight status in preschool. J Dev Behav Pediatr. Oct 2008;29(5):403–10. doi:10.1097/DBP.0b013e318182a976.18714209 | Study design
410 | Hui LL, Nelson EA, Yu LM, Li AM, Fok TF. Risk factors for childhood overweight in 6- to 7-y-old Hong Kong children. Int J Obes Relat Metab Disord. Nov 2003;27(11):1411–8. doi:10.1038/sj.ijo.0802423.14574354 | Study design; Country
411 | Humenikova L, Gates GE. Social and physical environmental factors and child overweight in a sample of American and Czech school-aged children: a pilot study. J Nutr Educ Behav. Jul-Aug 2008;40(4):251–7. doi:10.1016/j.jneb.2007.06.008.18565466 | Study design; Outcome
412 | Hunot-Alexander C, Curiel-Curiel CP, Romero-Velarde E, Intergenerational transmission of appetite: Associations between mother-child dyads in a Mexican population. Article. PLoS ONE. 2022;17(3 March)doi:10.1371/journal.pone.0264493 | Intervention/exposure; Outcome
413 | Hunsberger M; IDEFICS Consortium. Early feeding practices and family structure: associations with overweight in children. Proc Nutr Soc. 2014;73(1):132–136. doi:10.1017/S0029665113003741 24507855 | Study design; Intervention/exposure
414 | Hurley KM, Black MM, Papas MA, Caulfield LE. Maternal symptoms of stress, depression, and anxiety are related to nonresponsive feeding styles in a statewide sample of WIC participants. J Nutr. Apr 2008;138(4):799–805.. doi:10.1093/jn/138.4.799.18356338 | Study design
415 | Hurley KM, Pepper MR, Candelaria M, Systematic development and validation of a theory-based questionnaire to assess toddler feeding. J Nutr. Dec 2013;143(12):2044–9. doi:10.3945/jn.113.179846.24068792 | Study design; Intervention/exposure
416 | Huxtable A, Millar L, Love P, Bell C, Whelan J. Parental Translation into Practice of Healthy Eating and Active Play Messages and the Impact on Childhood Obesity: A Mixed Methods Study. Nutrients. Apr 27 2018;10(5)doi:10.3390/nu10050545. | Study design; Intervention/exposure
417 | Iguacel I, Michels N, Ahrens W, Prospective associations between socioeconomically disadvantaged groups and metabolic syndrome risk in European children. Results from the IDEFICS study. Int J Cardiol. Dec 1 2018;272:333–340. doi:10.1016/j.ijcard.2018.07.053.30017513 | Intervention/exposure; Outcome
418 | Ihmels MA, Welk GJ, Eisenmann JC, Nusser SM. Development and preliminary validation of a Family Nutrition and Physical Activity (FNPA) screening tool. Int J Behav Nutr Phys Act. Mar 12 2009;6:14.. doi:10.1186/1479-5868-6-14.19284631 | Study design
419 | Ip EH, Marshall SA, Arcury TA, Child Feeding Style and Dietary Outcomes in a Cohort of Latino Farmworker Families. J Acad Nutr Diet. Jul 2018;118(7):1208–1219. doi:10.1016/j.jand.2017.07.024.28966049 | Study design
420 | Jackson LW. The most important meal of the day: why children skip breakfast and what can be done about it. Pediatr Ann. 2013;42(9):184–187. doi:10.3928/00904481-20130823-10 | Study design
421 | Jacobs MP, Fiese BH. Family mealtime interactions and overweight children with asthma: potential for compounded risks?. J Pediatr Psychol. 2007;32(1):64–68. doi:10.1093/jpepsy/jsl026 16951307 | Study design; Outcome
422 | Jalali-Farahani S, Amiri P, Akbar HM, Cheraghi L, Karimi M, Azizi F. Effects of a Healthy Lifestyle Education on the Incidence of Metabolic Syndrome in Children during a 13-Year Follow-up. Int J Behav Med. 2018;25(1):131–140. doi:10.1007/s12529-017-9680-1 28795355 | Intervention/exposure
423 | James KS, Connelly CD, Gracia L, Mareno N, Baietto J. Ways to Enhance Children's Activity and Nutrition (WE CAN) - a pilot project with Latina mothers. J Spec Pediatr Nurs. Oct 2010;15(4):292–300.doi:10.1111/j.1744-6155.2010.00252.x.20880277 | Study design; Intervention/exposure
424 | Jang M, Brandon D, Vorderstrasse A. Relationships Among Parental Psychological Distress, Parental Feeding Practices, Child Diet, and Child Body Mass Index. Nurs Res. Jul/Aug 2019;68(4):296–306.. doi:10.1097/NNR.0000000000000344.30913169 | Study design
425 | Jang SH, Hwang H. Multilevel Factors Associated with Obesity among South Korean Adolescents before and during the COVID-19 Pandemic. Article in Press. Childhood obesity (Print). 2022. doi:10.1089/chi.2022.0053. | Study design; Intervention/exposure
426 | Jani R, Mallan KM, Daniels L. Association between Australian-Indian mothers' controlling feeding practices and children's appetite traits. Appetite. Jan 2015;84:188–95. doi:10.1016/j.appet.2014.10.020.25451580 | Study design
427 | Janicke DM, Lim CS, Perri MG, Featured Article: Behavior Interventions Addressing Obesity in Rural Settings: The E-FLIP for Kids Trial. J Pediatr Psychol. Sep 1 2019;44(8):889–901. doi:10.1093/jpepsy/jsz029.31039250 | Intervention/exposure
428 | Jansen E, Byrne R, Mallan K, Daniels L. From upset to calm but overweight in 3 steps: is food to calm early on related to the development of overeating and overweight in the preschool years? Journal article; Conference proceeding. Obesity facts. 2018;11:33. | Publication status
429 | Jansen E, Mallan KM, Nicholson JM, Daniels LA. The feeding practices and structure questionnaire: construction and initial validation in a sample of Australian first-time mothers and their 2-year olds. Int J Behav Nutr Phys Act. Jun 4 2014;11:72.24898364 | Study design
430 | Jansen E, Mulkens S, Emond Y, Jansen A. From the Garden of Eden to the land of plenty. Restriction of fruit and sweets intake leads to increased fruit and sweets consumption in children. Appetite. Nov 2008;51(3):570–5. doi:10.1016/j.appet.2008.04.012.18501474 | Outcome
431 | Jansen E, Mulkens S, Jansen A. Do not eat the red food!: prohibition of snacks leads to their relatively higher consumption in children. Appetite. Nov 2007;49(3):572–7. doi:10.1016/j.appet.2007.03.229.17490786 | Outcome
432 | Jansen E, Mulkens S, Jansen A. Tackling childhood overweight: treating parents exclusively is effective. Int J Obes (Lond). Apr 2011;35(4):501–9. doi:10.1038/ijo.2011.16.21364527 | Intervention/exposure; Outcome
433 | Jansen PW, Derks IPM, Batenburg A, Using Food to Soothe in Infancy is Prospectively Associated with Childhood BMI in a Population-Based Cohort. J Nutr. May 1 2019;149(5):788–794. doi:10.1093/jn/nxy277.30989177 | Age of all participants at intervention/exposure
434 | Javaras KN, Armstrong JM, Klein MH, Essex MJ, Davidson RJ, Goldsmith HH. Sex Differences in the Relationship Between Childhood Self-Regulation and Adolescent Adiposity. Obesity (Silver Spring). Sep 2020;28(9):1761–1769. doi:10.1002/oby.22926.32767554 | Study design; Intervention/exposure
435 | Jiang H, Li M, Wen LM, A Community-Based Short Message Service Intervention to Improve Mothers' Feeding Practices for Obesity Prevention: Quasi-Experimental Study. JMIR Mhealth Uhealth. Jun 3 2019;7(6):e13828. doi:10.2196/13828.31162133 | Intervention/exposure
436 | Jiang HJ, Li ML, Wen LMW, Effect of short message service intervention on children's BMI at 12 and 24 months and factors associated with BMI at 24 months: a community-based intervention in Shanghai, China. Journal article. Obesity reviews. 2016;17(Suppl 2):155. | Publication status
437 | Johannsen DL, Johannsen NM, Specker BL. Influence of parents' eating behaviors and child feeding practices on children's weight status. Obesity (Silver Spring). Mar 2006;14(3):431–9. doi:10.1038/oby.2006.57.16648614 | Study design
438 | Johnson CM, Henderson MS, Tripicchio G, Observed parent-child feeding dynamics in relation to child body mass index and adiposity. Pediatr Obes. Apr 2018;13(4):222–231. doi:10.1111/ijpo.12209.28296242 | Study design
439 | Johnson JG, Cohen P, Kasen S, Brook JS. Childhood adversities associated with risk for eating disorders or weight problems during adolescence or early adulthood. Am J Psychiatry. Mar 2002;159(3):394–400. doi:10.1176/appi.ajp.159.3.394.11870002 | Intervention/exposure; Outcome
440 | Jones BL, Fiese BH. Parent routines, child routines, and family demographics associated with obesity in parents and preschool-aged children. Front Psychol. 2014;5:374. doi:10.3389/fpsyg.2014.00374.24808883 | Study design
441 | Jones CH, Pollard TM, Summerbell CD, Ball H. Could parental rules play a role in the association between short sleep and obesity in young children? J Biosoc Sci. May 2014;46(3):405–18. doi:10.1017/s0021932013000291.23750569 | Study design
442 | Jonsson M, van Doorn J, van den Berg J. Parents' perceptions of eating skills of pre-term vs full-term infants from birth to 3 years. Int J Speech Lang Pathol. Dec 2013;15(6):604–12. doi:10.3109/17549507.2013.808699.24007388 | Intervention/exposure; Outcome
443 | Joosse L, Stearns M, Anderson H, Hartlaub P, Euclide J. Fit Kids/Fit Families: a report on a countywide effort to promote healthy behaviors. Wmj. Aug 2008;107(5):231–6.18777991 | Study design; Intervention/exposure
444 | Joyce JL, Zimmer-Gembeck MJ. Parent feeding restriction and child weight. The mediating role of child disinhibited eating and the moderating role of the parenting context. Appetite. Jun 2009;52(3):726–734. doi:10.1016/j.appet.2009.03.015.19501772 | Study design
445 | Juhari NA, Chin YS. Paternal education level and emotional regulation in parental feeding were associated with cognitive performance in a sample of preschoolers in Selangor. Article. Pakistan Journal of Nutrition. 2019;18(12):1120–1127. doi:10.3923/pjn.2019.1120.1127. | Study design
446 | Jungwon M, Wang VHC, Hong X, Jie M, Youfa W. Maternal perception of child overweight status and its association with weight-related parenting practices, their children's health behaviours and weight change in China. Public Health Nutrition. 2017;20(12):2096–2103.28583222 | Intervention/exposure
447 | Juton C, Berruezo P, Torres S, Association between Meal Frequency and Weight Status in Spanish Children: A Prospective Cohort Study. Nutrients. Feb 8 2023;15(4)doi:10.3390/nu15040870. | Intervention/exposure
448 | Kalavainen M, Utriainen P, Vanninen E, Korppi M, Nuutinen O. Impact of childhood obesity treatment on body composition and metabolic profile. Journal article. World journal of pediatrics. 2012;8(1):31–37.22105574 | Intervention/exposure
449 | Kanpheungton S. Psychometric study of the Child Feeding Questionnaire (TH-CFQ) among Thai parents of preschoolers. 2010;(Ph.D.):164 p–164 p. | Publication status
450 | Kasemsup R, Reicks M. The relationship between maternal child-feeding practices and overweight in Hmong preschool children. Ethn Dis. Winter 2006;16(1):187–93. | Study design
451 | Katz I, Madjar N, Harari A. Parental support and adolescent motivation for dieting: the Self-Determination Theory perspective. J Psychol. 2015;149(5):461–79. doi:10.1080/00223980.2014.903890.25975574 | Study design; Intervention/exposure
452 | Kavanagh KF, Cohen RJ, Heinig MJ, Dewey KG. Educational intervention to modify bottle-feeding behaviors among formula-feeding mothers in the WIC program: impact on infant formula intake and weight gain. J Nutr Educ Behav. Jul-Aug 2008;40(4):244–50. doi:10.1016/j.jneb.2007.01.002.18565465 | Age of all participants at intervention/exposure
453 | Keery H, Eisenberg ME, Boutelle K, Neumark-Sztainer D, Story M. Relationships between maternal and adolescent weight-related behaviors and concerns: the role of perception. J Psychosom Res. Jul 2006;61(1):105–11. doi:10.1016/j.jpsychores.2006.01.011.16813852 | Study design; Outcome
454 | Keihner AJ, Mitchell PR, Kitzmann C, Sugerman S, Foerster SB. Psychosocial, socioeconomic, behavioral, and environmental risk factors for BMI and overweight among 9- to 11-year-old children. Californian Journal of Health Promotion. 2009;7(S1):1–20. | Study design; Intervention/exposure
455 | Keller KL, Pietrobelli A, Johnson SL, Faith MS. Maternal restriction of children's eating and encouragements to eat as the 'non-shared environment': a pilot study using the child feeding questionnaire. Int J Obes (Lond). Nov 2006;30(11):1670–5. doi:10.1038/sj.ijo.0803318.16568136 | Study design
456 | Kennedy GA, Klein KM, Keel PK. Prevalence and predictors of parental concern for children's weight from 2002 to 2012. Public Health. Sep 2018;162:58–62. doi:10.1016/j.puhe.2018.05.021.29975861 | Intervention/exposure; Outcome
457 | Kersey M, Lipton R, Quinn MT, Lantos JD. Overweight in Latino preschoolers: do parental health beliefs matter? Am J Health Behav. May-Jun 2010;34(3):340–8. doi:10.5993/ajhb.34.3.9.20001191 | Study design
458 | Keski-Rahkonen A, Kaprio J, Rissanen A, Virkkunen M, Rose RJ. Breakfast skipping and health-compromising behaviors in adolescents and adults. Eur J Clin Nutr. Jul 2003;57(7):842–53.. doi:10.1038/sj.ejcn.1601618.12821884 | Study design; Intervention/exposure
459 | Khalsa AS, Copeland KA, Kharofa RY, Geraghty SR, Dewitt TG, Woo JG. The Longitudinal Relation between Infant Feeding Styles and Growth Trajectories among Families from Low-Income Households. J Nutr. 2022;152(9):2015–2022. doi:10.1093/jn/nxac123 35641195 | Age of all participants at intervention/exposure
460 | Khanal S, Welsby D, Lloyd B, Innes-Hughes C, Lukeis S, Rissel C. Effectiveness of a once per week delivery of a family-based childhood obesity intervention: a cluster randomised controlled trial. Pediatr Obes. Dec 2016;11(6):475–483. doi:10.1111/ijpo.12089.26695932 | Intervention/exposure
461 | Khashayar P, Kasaeian A, Heshmat R, Childhood Overweight and Obesity and Associated Factors in Iranian Children and Adolescents: A Multilevel Analysis; the CASPIAN-IV Study. Front Pediatr. 2018;6:393.. doi:10.3389/fped.2018.00393.30622935 | Study design
462 | Kheirollahpour M, Shohaimi S. Dimensional model for estimating factors influencing childhood obesity: path analysis based modeling. ScientificWorldJournal. 2014;2014:512148. doi:10.1155/2014/512148.25097878 | Study design
463 | Kilanowski JF, Lin L. Effects of a healthy eating intervention on Latina migrant farmworker mothers. Fam Community Health. Oct-Dec 2013;36(4):350–62. doi:10.1097/FCH.0b013e31829d277e.23986075 | Study design; Intervention/exposure
464 | Kilaru A, Griffiths PL, Ganapathy S, Ghosh S. Community-based nutrition education for improving infant growth in rural Karnataka. Indian Pediatr. May 2005;42(5):425–32.15923688 | Country
465 | Kim HS, Park J, Park KY, Lee MN, Ham OK. Parent Involvement Intervention in Developing Weight Management Skills for both Parents and Overweight/Obese Children. Asian Nurs Res (Korean Soc Nurs Sci). Mar 2016;10(1):11–7. doi:10.1016/j.anr.2015.07.006.27021829 | Intervention/exposure
466 | Kim JH, Bost KK. Self-regulation linking the quality of early parent-child relationship to adolescents' obesity risk and food consumption. Pediatr Obes. Mar 2023;18(3):e12993. doi:10.1111/ijpo.12993.36479850 | Intervention/exposure
467 | Kim KW, Wallander JL, Felt JM, Elliott MN, Schuster MA. Associations of Parental General Monitoring with Adolescent Weight-Related Behaviors and Weight Status. Obesity (Silver Spring). Feb 2019;27(2):280–287. doi:10.1002/oby.22372.30597754 | Intervention/exposure
468 | Kim MJ, McIntosh WA, Anding J, Kubena KS, Reed DB, Moon GS. Perceived parenting behaviours predict young adolescents' nutritional intake and body fatness. Matern Child Nutr. Oct 2008;4(4):287–303. doi:10.1111/j.1740-8709.2008.00142.x.18811793 | Study design
469 | Kim-Herrera EY, Ramírez-Silva I, Rodríguez-Oliveros G, Parental Feeding Styles and Their Association With Complementary Feeding Practices and Growth in Mexican Children. Front Pediatr. 2021;9:786397. Published 2021 Dec 21. doi:10.3389/fped.2021.786397 34993164 | Age of all participants at intervention/exposure
470 | Kirschenbaum DS, Germann JN, Rich BH. Treatment of morbid obesity in low-income adolescents: effects of parental self-monitoring. Obes Res. Sep 2005;13(9):1527–9.. doi:10.1038/oby.2005.187.16222054 | Study design; Intervention/exposure
471 | Kittiya R, Chintana W. Effectiveness of a Family-Based Behavioral Counseling Program among School-aged Children with Obesity: A Quasi-Experimental Study. Pacific Rim International Journal of Nursing Research. 2021;25(3):466–480. | Intervention/exposure
472 | Kleber M, Schaefer A, Winkel K, Lifestyle intervention "Obeldicks Mini" for obese children aged 4 to 7 years. Klin Padiatr. 2009;221(5):290–294. doi:10.1055/s-0029-1234129 19707991 | Intervention/exposure
473 | Klosowska J, De Henauw S, Verbeken S, Braet C, Wijnant K, Michels N. The influence of parents on childhood weight status: relation with eating behaviour. Proceedings of the Nutrition Society. 2020;79(OCE2):1–1. | Publication status
474 | Knowlden AP, Conrad E. Two-Year Outcomes of the Enabling Mothers to Prevent Pediatric Obesity Through Web-Based Education and Reciprocal Determinism (EMPOWER) Randomized Control Trial. Health Educ Behav. Apr 2018;45(2):262–276. doi:10.1177/1090198117732604.28954544 | Intervention/exposure; Outcome
475 | Kong A, Vijayasiri G, Fitzgibbon ML, Schiffer LA, Campbell RT. Confirmatory factor analysis and measurement invariance of the Child Feeding Questionnaire in low-income Hispanic and African-American mothers with preschool-age children. Appetite. Jul 2015;90:16–22. doi:10.1016/j.appet.2015.02.027.25728882 | Study design
476 | Kong KL, Eiden RD, Paluch RA. Early Nonfood Parent-Infant Interactions and Development of Obesity in a High-Risk, Diverse Sample. Obesity (Silver Spring). Nov 2019;27(11):1754–1760. doi:10.1002/oby.22649.31689006 | Age of all participants at intervention/exposure
477 | Kramer MS, Moodie EE, Platt RW. Infant feeding and growth: can we answer the causal question? Journal article. Epidemiology (Cambridge, Mass). 2012;23(6):790–794. doi:10.1097/EDE.0b013e31826cc0e9.23038108 | Study design; Intervention/exposure
478 | Kramer RF, Coutinho AJ, Vaeth E, Christiansen K, Suratkar S, Gittelsohn J. Healthier home food preparation methods and youth and caregiver psychosocial factors are associated with lower BMI in African American youth. J Nutr. May 2012;142(5):948–54. doi:10.3945/jn.111.156380.22457390 | Study design
479 | Kravets M, Sullivan JA, Parrott A, Eating Competence Among Caregivers of Toddlers: Associations With Caregiver and Child Overweight/Obesity [published correction appears in J Nutr Educ Behav. 2023 Feb;55(2):164. doi: 10.1016/j.jneb.2022.12.005]. J Nutr Educ Behav. 2022;54(8):745–752. doi:10.1016/j.jneb.2022.02.020 35668000 | Intervention/exposure
480 | Kröller K, Warschburger P. Maternal feeding strategies and child's food intake: considering weight and demographic influences using structural equation modeling. Int J Behav Nutr Phys Act. 2009;6:78. Published 2009 Nov 22. doi:10.1186/1479-5868-6-78 19930607 | Study design; Outcome
481 | Kronborg H, Foverskov E, Vaeth M. Predictors for early introduction of solid food among Danish mothers and infants: an observational study. BMC Pediatr. 2014;14:243. Published 2014 Oct 1. doi:10.1186/1471-2431-14-243 25270266 | Study design; Outcome
482 | Kroon Van Diest AM, Tylka TL. The Caregiver Eating Messages Scale: Development and psychometric investigation. Body Image. Sep 2010;7(4):317–26. doi: 10.1016/j.bodyim.2010.06.002.20634160 | Study design; Intervention/exposure; Outcome
483 | Krug I, Villarejo C, Jimenez-Murcia S, Eating-related environmental factors in underweight eating disorders and obesity: are there common vulnerabilities during childhood and early adolescence? Eur Eat Disord Rev. May 2013;21(3):202–8. doi: 10.1002/erv.2204.23172786 | Study design
484 | Kubik MY, Lee J, Fulkerson JA, Gurvich OV, Sirard JR. School-Based Secondary Obesity Prevention for Eight- to Twelve-Year-Olds: Results from the Students, Nurses, and Parents Seeking Healthy Options Together Randomized Trial. Child Obes. Apr 2021;17(3):185–195. doi:10.1089/chi.2020.0321.33601934 | Intervention/exposure
485 | Kugler KC, Balantekin KN, Birch LL, Savage JS. Application of the multiphase optimization strategy to a pilot study: an empirical example targeting obesity among children of low-income mothers. BMC Public Health. Nov 22 2016;16(1):1181. doi:10.1186/s12889-016-3850-y.27876027 | Intervention/exposure; Outcome
486 | Kulik N, Valle CG, Tate DF. Friend and Family Support for Weight Loss in Adolescent Females. Child Obes. Feb 2016;12(1):44–51. doi:10.1089/chi.2015.0044.26584254 | Intervention/exposure
487 | Kumar S, Croghan IT, Biggs BK, Family-Based Mindful Eating Intervention in Adolescents with Obesity: A Pilot Randomized Clinical Trial. Journal article. Children (Basel, Switzerland). 2018;5(7). doi:10.3390/children5070093. | Intervention/exposure
488 | Küpers LK, e Pijper J J, Sauer PJ, Stolk RP, Corpeleijn E. Skipping breakfast and overweight in 2- and 5-year-old Dutch children-the GECKO Drenthe cohort. Int J Obes (Lond). Apr 2014;38(4):569–71doi:10.1038/ijo.2013.194.24158122 | Intervention/exposure
489 | Kuriakose JR. Nutritional status and feeding practices of infants. Nursing Journal of India. 2010;101(8):5p–5p. | Publication status
490 | Kuswara K, Laws R, Kremer P, Hesketh KD, Campbell KJ. The infant feeding practices of Chinese immigrant mothers in Australia: A qualitative exploration. Obesity Research & Clinical Practice. 2019;13(1):91–92. doi:10.1016/i.orcp.2016.10.247. | Study design; Intervention/exposure
491 | Laessle R, Lehrke S. Effectiveness of a Family Treatment Compared to Behaviorally Oriented Group Treatment in Obese Children. Journal article. Verhaltenstherapie. 2022;32(4):230–236. doi:10.1159/000524673. | Publication language
492 | Laessle RG, Uhl H, Lindel B, Müller A. Parental influences on laboratory eating behavior in obese and non-obese children. Int J Obes Relat Metab Disord. May 2001;25 Suppl 1:S60–2. doi:10.1038/sj.ijo.0801701.11466591 | Intervention/exposure; Outcome
493 | Laessle RG, Uhl H, Lindel B. Parental influences on eating behavior in obese and nonobese preadolescents. Int J Eat Disord. Dec 2001;30(4):447–53. doi: 10.1002/eat.1106.11746306 | Intervention/exposure; Outcome
494 | Lakshman RR, Landsbaugh JR, Schiff A, Hardeman W, Ong KK, Griffin SJ. Development of a questionnaire to assess maternal attitudes towards infant growth and milk feeding practices. Int J Behav Nutr Phys Act. 2011;8:35. Published 2011 Apr 21. doi: 10.1186/1479-5868-8-35 21510900 | Intervention/exposure; Outcome
495 | Lakshman R, Clifton EA, Ong KK. Baby-Led Weaning-Safe and Effective but Not Preventive of Obesity. JAMA Pediatrics. 2017;171(9):832–833. doi:10.1001/jamapediatrics.2017.1766.28692709 | Study design
496 | Lanigan JD. The relationship between practices and child care providers' beliefs related to child feeding and obesity prevention. J Nutr Educ Behav. Nov-Dec 2012;44(6):521–9. doi:10.1016/j.ineb.2011.07.008.22559927 | Intervention/exposure; Outcome
497 | Larios SE, Ayala GX, Arredondo EM, Baquero B, Elder JP. Development and validation of a scale to measure Latino parenting strategies related to children's obesigenic behaviors. The parenting strategies for eating and activity scale (PEAS). Appetite. Feb 2009;52(1):166–72. doi:10.1016/j.appet.2008.09.011.18845197 | Study design
498 | Larsen JK, Karssen LT, van der Veek SMC. Targeting food parenting practices to prevent early child obesity risk requires a different approach in families with a lower socioeconomic position. Front Public Health. 2022;10:1012509. doi:10.3389/fpubh.2022.1012509.36225771 | Study design
499 | Larsen JK, Sleddens EFC, Vink JM, Fisher JO, Kremers SPJ. General Parenting Styles and Children's Obesity Risk: Changing Focus. Front Psychol. 2018;9:2119. doi:10.3389/fpsyg.2018.02119.30459686 | Study design
500 | Larson N, Eisenberg ME, Berge JM, Arcan C, Neumark-Sztainer D. Ethnic/racial disparities in adolescents' home food environments and linkages to dietary intake and weight status. Eat Behav. Jan 2015;16:43–6. doi:10.1016/j.eatbeh.2014.10.010.25464066 | Study design
501 | Larson N, Eisenberg ME, Berge JM, Arcan C, Neumark-Sztainer D. 178. Family and Home Food Environments of Ethnically/Racially Diverse Adolescents in Minnesota: Disparities and Linkages to Dietary Intake and Weight Status. Journal of Adolescent Health. 2015;56:S91–2. doi:10.1016/j.jadohealth.2014.10.183. | Publication status
502 | Lavner JA, Savage JS, Stansfield BK, Effects of the Sleep SAAF responsive parenting intervention on rapid infant weight gain: A randomized clinical trial of African American families. Appetite. 2022;175:106080. doi:10.1016/j.appet.2022.106080 35577176 | Intervention/exposure
503 | Lawrence E, Mollborn S, Riosmena F. Early Childhood Disadvantage for Sons of Mexican Immigrants: Body Mass Index Across Ages 2–5. Am J Health Promot. Sep 2016;30(7):545–53. doi:10.4278/ajhp.140725-QUAN-366.26305614 | Study design; Intervention/exposure
504 | Layte R, Bennett A, McCrory C, Kearney J. Social class variation in the predictors of rapid growth in infancy and obesity at age 3 years. Int J Obes (Lond). Jan 2014;38(1):82–90. doi:10.1038/ijo.2013.160.23979218 | Intervention/exposure
505 | Lee H, Oldewage-Theron W, Dawson JA. Effects of a Theory-Based, Multicomponent eHealth Intervention for Obesity Prevention in Young Children from Low-Income Families: A Pilot Randomized Controlled Study. Nutrients. May 13 2023;15(10)doi:10.3390/nu15102296. | Intervention/exposure; Outcome
506 | Lee HA, Lee WK, Kong KA, The effect of eating behavior on being overweight or obese during preadolescence. J Prev Med Public Health. Sep 2011;44(5):226–33. doi:10.3961/jpmph.2011.44.5.226.22020188 | Study design
507 | Lee HJ, Lee SY, Park EC. Do family meals affect childhood overweight or obesity?: nationwide survey 2008–2012. Pediatr Obes. Jun 2016;11(3):161–5. doi:10.1111/ijpo.12035.26061428 | Study design
508 | Lee HY, Song IH, Kawachi I. Maternal and child social support and food availability in relation to child growth in four low- and middle-income countries. Article. Scientific reports. 2022;12(1):5910. doi:10.1038/s41598-022-09850-1.35396562 | Study design; Intervention/exposure
509 | Lee Y, Mitchell DC, Smiciklas-Wright H, Birch LL. Diet quality, nutrient intake, weight status, and feeding environments of girls meeting or exceeding recommendations for total dietary fat of the American Academy of Pediatrics. Pediatrics. Jun 2001;107(6):E95. doi:10.1542/peds.107.6.e95.11389293 | Study design; Outcome
510 | Lehto R, Ray C, Roos E. Longitudinal associations between family characteristics and measures of childhood obesity. Int J Public Health. 2012;57(3):495–503. doi:10.1007/s00038-011-0281-5 21814847 | Age of all participants at intervention/exposure
511 | Lelakowska G, Kanya MJ, Balassone BR, Toddlers' impulsivity, inhibitory control, and maternal eating-related supervision in relation to toddler body mass index: Direct and interactive effects. Appetite. Nov 1 2019;142:104343. doi:10.1016/j.appet.2019.104343.31276711 | Study design
512 | Lent M, Hill TF, Dollahite JS, Wolfe WS, Dickin KL. Healthy children, healthy families: parents making a difference! A curriculum integrating key nutrition, physical activity, and parenting practices to help prevent childhood obesity. J Nutr Educ Behav. Jan-Feb 2012;44(1):90–2. doi:10.1016/j.jneb.2011.02.011.21900051 | Study design; Intervention/exposure
513 | Lev-Ari L, Zohar AH. Nothing gained: an explorative study of the long-term effects of perceived maternal feeding practices on women's and men's adult BMI, body image dissatisfaction, and disordered eating. Int J Psychol. 2013;48(6):1201–11. doi:10.1080/00207594.2013.779378.23547649 | Study design
514 | Lev-Ari L, Zohar AH. The psychometric properties of the Retrospective Child Feeding Questionnaire in Hebrew. Appetite. Jun 2013;65:14–9. doi:10.1016/j.appet.2013.01.007.23376732 | Study design; Outcome
515 | Levy Y, Levy A, Zangen T, Diagnostic clues for identification of nonorganic vs organic causes of food refusal and poor feeding. J Pediatr Gastroenterol Nutr. Mar 2009;48(3):355–62. doi:10.1097/mpg.0b013e31818b1936.19274791 | Intervention/exposure; Outcome
516 | Lewis JA, Hayman LL. TOWARD EVIDENCE- BASED PRACTICE. Parent Diet Modification, Child Activity or Both in Obese Children: An RCT. MCN: The American Journal of Maternal Child Nursing. 2012;37(1):69–69. | Publication status
517 | Lewis M, Worobey J. Mothers and toddlers lunch together. The relation between observed and reported behavior. Appetite. Jun 2011;56(3):732–6. doi:10.1016/j.appet.2011.02.011.21349305 | Study design; Outcome
518 | Li Ming W. A bottle-weaning counselling intervention for parents of 12-month-old infants reduces bottle use at age 24 months but has no effect on child weight. Journal article. Evidence based nursing. 2015;18(1):14–14. doi:10.1136/eb-2014-101825.24858441 | Study design; Intervention/exposure
519 | Li M, Dibley MJ, Sibbritt D, Yan H. Factors associated with adolescents' overweight and obesity at community, school and household levels in Xi'an City, China: results of hierarchical analysis. Eur J Clin Nutr. May 2008;62(5):635–43. doi:10.1038/sj.ejcn.1602757.17440524 | Study design; Intervention/exposure
520 | Li R, Fein SB, Grummer-Strawn LM. Association of breastfeeding intensity and bottle-emptying behaviors at early infancy with infants' risk for excess weight at late infancy. Pediatrics. Oct 2008;122 Suppl 2:S77–84. doi:10.1542/peds.2008-1315j.18829835 | Age of all participants at intervention/exposure
521 | Liang J, Matheson BE, Rhee KE, Peterson CB, Rydell S, Boutelle KN. Parental control and overconsumption of snack foods in overweight and obese children. Appetite. May 1 2016;100:181–8. doi:10.1016/j.appet.2016.02.030.26911259 | Study design
522 | Liang T, Kuhle S, Veugelers PJ. Nutrition and body weights of Canadian children watching television and eating while watching television. Public Health Nutr. Dec 2009;12(12):2457–63. doi:10.1017/s1368980009005564.19405988 | Study design
523 | Liew J, Zhou Z, Perez M, Yoon M, Kim M. Parental Child-feeding in the Context of Child Temperament and Appetitive Traits: Evidence for a Biopsychosocial Process Model of Appetite Self-Regulation and Weight Status. Nutrients. Oct 30 2020;12(11)doi:10.3390/nu12113353. | Study design
524 | Lim S, Zoellner JM, Ajrouch KJ, Ismail AI. Overweight in childhood: the role of resilient parenting in African-American households. Am J Prev Med. Mar 2011;40(3):329–33. doi:10.1016/j.amepre.2010.11.006.21335265 | Intervention/exposure
525 | Lin D, Chen D, Huang J, Pre-Birth and Early-Life Factors Associated With the Timing of Adiposity Peak and Rebound: A Large Population-Based Longitudinal Study. Front Pediatr. 2021;9:742551. doi:10.3389/fped.2021.742551.35004537 | Intervention/exposure
526 | Ling J, Zahry NR, Robbins LB. Dose-Response Relationship in a Healthy Habits Study for Head Start Preschoolers. Nurs Res. Jul/Aug 2019;68(4):329–335. doi:10.1097/nnr.0000000000000345.30789546 | Intervention/exposure
527 | Lioret S, Campbell K, McNaughton S, Parent focused intervention impacts obesity risk behaviours in infants: results of the melbourne infant program cluster-randomised controlled trial. Journal article; Conference proceeding. Obesity facts. 2012;5:33. | Publication status
528 | Lioret S, Cameron AJ, McNaughton SA, Association between maternal education and diet of children at 9 months is partially explained by mothers' diet. Matern Child Nutr. Oct 2015;11(4):936–47. doi:10.1111/mcn.12031.23560743 | Intervention/exposure
529 | Lipsky LM, Burger K, Cummings JR, Faith MS, Nansel TR. Associations of parent feeding behaviors and early life food exposures with early childhood appetitive traits in an observational cohort study. Physiol Behav. Jun 1 2023;265:114175. doi:10.1016/j.physbeh.2023.114175.36997010 | Outcome
530 | Liszewska N, Scholz U, Radtke T, Horodyska K, Luszczynska A. Bi-directional associations between parental feeding practices and children's body mass in parent-child dyads. Appetite. Oct 1 2018;129:192–197. doi:10.1016/j.appet.2018.07.011.30017947 | Age of all participants at intervention/exposure
531 | Liu WH, Malian KM, Mihrshahi S, Daniels LA. Feeding beliefs and practices of Chinese immigrant mothers. Validation of a modified version of the child feeding questionnaire. Appetite. Sep 2014;80:55–60. doi:10.1016/j.appet.2014.04.030.24816321 | Study design
532 | Lloyd AB, Lubans DR, Plotnikoff RC, Morgan PJ. Impact of the 'Healthy Dads, Healthy Kids' lifestyle programme on the activity- and diet-related parenting practices of fathers and mothers. Pediatr Obes. Dec 2014;9(6):e149–55. doi:10.1111/ijpo.248.24980063 | Intervention/exposure; Outcome
533 | Lloyd AB, Lubans DR, Plotnikoff RC, Collins CE, Morgan PJ. A comparison of maternal and paternal parenting practices and their influence on children's physical activity, screen-time, diet and adiposity...Australian & New Zealand Obesity Society Annual Scientific Meeting, October 17–19, 2013, Melbourne, Victoria. Obesity Research & Clinical Practice. 2013;7:e103–e104. | Study design
534 | Lohman BJ, Gillette MT, Neppl TK. Harsh Parenting and Food Insecurity in Adolescence: The Association With Emerging Adult Obesity. J Adolesc Health. Jul 2016;59(1):123–7. doi:10.1016/j.jadohealth.2016.03.024.27185622 | Intervention/exposure
535 | Looney SM, Raynor HA. Impact of Portion Size and Energy Density on Snack Intake in Preschool-Aged Children. Journal of the American Dietetic Association. 2011;111(3):414–418. doi:10.1016/j.jada.2010.11.016.21338741 | Intervention/exposure; Outcome
536 | Lopez NV, Ayala GX, Corder K, Parent support and parent-mediated behaviors are associated with children's sugary beverage consumption. J Acad Nutr Diet. Apr 2012;112(4):541–7. doi:10.1016/j.jand.2011.11.013.22709703 | Study design; Outcome
537 | López-Barrón RG, Jiménez-Cruz A, Bacardí-Gascón M. Modifiable environmental obesity risk factors among elementary school children in a Mexico-us border city. Nutr Hosp. May 1 2015;31(5):2047–53. doi:10.3305/nh.2015.31.5.8669.25929373 | Study design
538 | Lora KR, Hubbs-Tait L, Ferris AM, Wakefield D. African-American and Hispanic children's beverage intake: Differences in associations with desire to drink, fathers' feeding practices, and weight concerns. Appetite. Dec 1 2016;107:558–567. doi:10.1016/j.appet.2016.09.012.27620644 | Study design
539 | Lorenzato L, Miranda Cruz IS, Braga Costa TM, Sousa Almeida S. Translation and CrossCultural Adaptation of a Brazilian Version of the Child Feeding Questionnaire. Paideia (0103863X). 2017;27(66):33–42. | Study design
540 | Loth KA, MacLehose RF, Fulkerson JA, Crow S, Neumark-Sztainer D. Are food restriction and pressure-to-eat parenting practices associated with adolescent disordered eating behaviors? Int J Eat Disord. Apr 2014;47(3):310–4. doi:10.1002/eat.22189.24105668 | Study design; Outcome
541 | Loth KA, MacLehose RF, Fulkerson JA, Crow S, Neumark-Sztainer D. Food-related parenting practices and adolescent weight status: a population-based study. Pediatrics. May 2013;131(5):e1443–50. doi:10.1542/peds.2012-3073.23610202 | Study design
542 | Lourengo BH, Villamor E, Augusto RA, Cardoso MA. Influence of early life factors on body mass index trajectory during childhood: a population-based longitudinal analysis in the Western Brazilian Amazon. Matern Child Nutr. Apr 2015;11(2):240–52. doi:10.1111/mcn.12005.23020806 | Intervention/exposure
543 | Lovan P, Lozano A, Estrada Y, The Role of Intervention Fidelity, Culture, and IndividualLevel Factors on Health-Related Outcomes Among Hispanic Adolescents with Unhealthy Weight: Findings from a Longitudinal Intervention Trial. Prev Sci. Apr 18 2023. doi:10.1007/s11121-023-01527-z. | Intervention/exposure
544 | Ludwig DS. Weight loss strategies for adolescents: a 14-year-old struggling to lose weight. Jama. Feb 1 2012;307(5):498–508. doi:10.1001/jama.2011.2011.22215761 | Study design
545 | Lumeng JC, Burke LM. Maternal prompts to eat, child compliance, and mother and child weight status. J Pediatr. Sep 2006;149(3):330–335. doi:10.1016/j.jpeds.2006.04.009.16939742 | Study design; Outcome
546 | Lumeng JC, Miller AL, Appugliese D, Rosenblum K, Kaciroti N. Picky eating, pressuring feeding, and growth in toddlers. Appetite. Apr 1 2018;123:299–305. doi:10.1016/j.appet.2017.12.020.29331364 | Age of all participants at intervention/exposure
547 | Lumeng JC, Ozbeki TN, Appugliese DP, Kaciroti N, Corwyn RF, Bradley RH. Observed assertive and intrusive maternal feeding behaviors increase child adiposity. Am J Clin Nutr. Mar 2012;95(3):640–7. doi:10.3945/ajcn.111.024851.22277552 | Age of all participants at intervention/exposure
548 | Lumeng JC. Infant Eating Behaviors and Risk for Overweight. JAMA. 2016;316(19):2036–2037. doi:10.1001/jama.2016.16899 27838708 | Study design
549 | Lumeng JC. Parental-adolescent conversations that focus on weight are more likely to be associated with unhealthy weight-control behaviours in adolescents than conversations that focus on healthy eating. Evid Based Nurs. 2014; 17(4): 110. doi:10.1136/eb-2013-101588 24531103 | Study design; Publication status
550 | Lydecker JA, Grilo CM. The apple of their eye: Attitudinal and behavioral correlates of parents' perceptions of child obesity. Obesity (Silver Spring). May 2016;24(5):1124–31. doi:10.1002/oby.21439.26916369 | Study design
551 | Lyons ER, Nekkanti AK, Funderburk BW, Skowron EA. Parent-Child Interaction Therapy Supports Healthy Eating Behavior in Child Welfare-Involved Children. Article. International journal of environmental research and public health. 2022;19(17). doi:10.3390/ijerph191710535 | Intervention/exposure
552 | Lytle LA, Hearst MO, Fulkerson J, Examining the relationships between family meal practices, family stressors, and the weight of youth in the family. Ann Behav Med. Jun 2011;41(3):353–62. doi:10.1007/s12160-010-9243-z.21136225 | Study design
553 | Ma JQ, Zhou LL, Hu YQ, Feeding and growth of normal birth weight infants during the first year of life in Shanghai. Early Hum Dev. 2012;88(10):831–836. doi:10.1016/j.earlhumdev.2012.06.003 22749637 | Study design
554 | Ma JQ, Zhou LL, Hu YQ, A summary index of infant and child feeding practices is associated with child growth in urban Shanghai. BMC Public Health. Jul 28 2012;12:568. doi:10.1186/1471-2458-12-568.22839527 | Intervention/exposure
555 | Ma JQ, Zhou LL, Hu YQ, Liu SS, Sheng XY. Association between feeding practices and weight status in young children. BMC Pediatr. Aug 26 2015;15:97. doi:10.1186/s12887-015-0418-4.26306490 | Country
556 | Ma L, Fang Z, Gao L, A 3-year Longitudinal Study of Pocket Money, Eating Behavior, Weight Status: The Childhood Obesity Study in China Mega-Cities. Int J Environ Res Public Health. Dec 7 2020;17(23)doi:10.3390/ijerph17239139. | Intervention/exposure; Age of all participants at intervention/exposure
557 | MacFarlane A, Cleland V, Crawford D, Campbell K, Timperio A. Longitudinal examination of the family food environment and weight status among children. Int J Pediatr Obes. 2009;4(4):343 52. doi: 10.3109/17477160902846211.19922051 | Age of all participants at intervention/exposure
558 | Machuca H, Arevalo S, Hackley B, Well Baby Group Care: Evaluation of a Promising Intervention for Primary Obesity Prevention in Toddlers. Child Obes. Jun 2016;12(3):171–8. doi:10.1089/chi.2015.0212.27035857 | Age of all participants at intervention/exposure
559 | Magarey AM, Perry RA, Baur LA, A parent-led family-focused treatment program for overweight children aged 5 to 9 years: the PEACH RCT. Journal article. Pediatrics. 2011;127(2):214–222. doi:10.1542/peds.2009-1432.21262890 | Intervention/exposure
560 | Mahmood L, Gonzalez-Gil EM, Makrilakis K, Cross-sectional and longitudinal associations between family meals frequency and children's overweight/obesity in families at high risk of type 2 diabetes: The Feel4Diabetes-study. Pediatr Obes. Apr 2023; 18(4):e13000. doi:10.1111/ijpo.13000.36632012 | Age of all participants at intervention/exposure
561 | Mais LA, Warkentin S, Latorre Mdo R, Carnell S, Taddei JA. Validation of the Comprehensive Feeding Practices Questionnaire among Brazilian Families of School-Aged Children. Front Nutr. 2015;2:35. doi:10.3389/fnut.2015.00035.26579525 | Study design; Outcome
562 | Malian KM, Daniels LA, de Jersey SJ. Confirmatory factor analysis of the Baby Eating Behaviour Questionnaire and associations with infant weight, gender and feeding mode in an _Australian sample. Appetite. 2014;82:43–49. doi:10.1016/j.appet.2014.06.026 25009080 | Study design; Intervention/exposure
563 | Malian KM, Daniels LA, Wilson JL, Jansen E, Nicholson JM. Association between maternal depressive symptoms in the early post-natal period and responsiveness in feeding at child age 2 years. Matern Child Nutr. Oct 2015;11(4):926–35. doi:10.1111/mcn.12116.24784325 | Outcome
564 | Malian KM, Fildes A, Magarey AM, Daniels LA. The Relationship between Number of Fruits, Vegetables, and Noncore Foods Tried at Age 14 Months and Food Preferences, Dietary Intake Patterns, Fussy Eating Behavior, and Weight Status at Age 3.7 Years. J Acad Nutr Diet. Apr 2016;116(4):630–7. doi:10.1016/j.jand.2015.06.006.26198582 | Intervention/exposure
565 | Mallan KM, Sullivan SE, e Jersey SJ, Daniels LA. The relationship between maternal feeding beliefs and practices and perceptions of infant eating behaviours at 4 months. Appetite. Oct 1 2016;105:1–7. doi:10.1016/j.appet.2016.04.032.27133549 | Study design
566 | Manios Y, Moschonis G, Androutsos O, Family sociodemographic characteristics as correlates of children's breakfast habits and weight status in eight European countries. The ENERGY (EuropeaN Energy balance Research to prevent excessive weight Gain among Youth) project. Public Health Nutr. Apr 2015; 18(5)774–83. doi:10.1017/s1368980014001219.25017807 | Study design
567 | Manzano MA, Strong DR, Rhee KE, Liang J, Boutelle KN. Discordance between assessments of food cue responsiveness: Implications for assessment in youth with overweight/obesity. Appetite. Jul 1 2023;186:106575. doi:10.1016/j.appet.2023.106575.37100119 | Study design; Intervention/exposure; Outcome
568 | Mårild S, Russo P, Veidebaum T, Impact of a community based health-promotion programme in 2- to 9-year-old children in Europe on markers of the metabolic syndrome, the IDEFICS study. Obes Rev. Dec 2015;16 Suppl 2:41–56. doi:10.1111/obr.12368.26707015 | Intervention/exposure
569 | Marques DCS, Ferreira WC, Santos IC, Impacts of a Multi-Professional Family versus Isolated Intervention on Food Level Processing in Overweight Adolescents: A Randomized Trial. Nutrients. Feb 13 2023;15(4). doi:10.3390/nu15040935. | Intervention/exposure
570 | Martin C, Apolzan J, Hawkins K, Hall L, Davis A, Chatham J. Efcacy of a home-based weight management intervention for 2–6 year old children and their parents: results of a randomized controlled pilot trial. Journal article; Conference proceeding. Obesity facts. 2017;10:233–234. | Publication status
571 | Marx JM, Hoffmann DA, Musher-Eizenman DR. Meals and snacks: Children's characterizations of food and eating cues. Appetite. Feb 1 2016;97:1–7. doi:10.1016/j.appet.2015.11.010.26585635 | Intervention/exposure; Outcome
572 | Mascola AJ, Bryson SW, Agras WS. Picky eating during childhood: a longitudinal study to age 11 years. Eat Behav. Dec 2010;11(4):253–7. doi:10.1016/j.eatbeh.2010.05.006.20850060 | Intervention/exposure
573 | Mason SM, Santaularia NJ, Berge JM, Larson N, Neumark-Sztainer D. Is the childhood home food environment a confounder of the association between child maltreatment exposure and adult body mass index? Prev Med. May 2018;110:86–92. doi:10.1016/j.ypmed.2018.02.016.29454080 | Intervention/exposure
574 | Mason TB. Parental instrumental feeding, negative affect, and binge eating among overweight individuals. Eat Behav. Apr 2015;17:107–10. doi:10.1016/j.eatbeh.2015.01.013.25682364 | Study design; Outcome
575 | Matheson DM, Robinson TN, Varady A, Killen JD. Do Mexican-American mothers' food-related parenting practices influence their children's weight and dietary intake? J Am Diet Assoc. Nov 2006;106(11):1861–5. doi:10.1016/j.jada.2006.08.004.17081838 | Study design
576 | Matthews-Ewald MR, Posada A, Wiesner M, Olvera N. An exploratory factor analysis of the Parenting strategies for Eating and physical Activity Scale (PEAS) for use in Hispanic mothers of adolescent and preadolescent daughters with overweight. Eat Behav. Dec 2015;19:193–9. doi:10.1016/j.eatbeh.2015.10.001.26519927 | Study design
577 | Matton A, Goossens L, Braet C, Van Durme K. Continuity in primary school children's eating problems and the influence of parental feeding strategies. J Youth Adolesc. 2013;42(1):52–66. doi:10.1007/s10964-012-9794-3 22801806 | Outcome
578 | Mayurachat K, Warunee F, Jutamas C, Patcharaporn A, Kennedy C. An Intervention Study of Changing Eating Behaviors and Reducing Weight in Thai Children Aged 10–12. Journal article. Pacific Rim international journal of nursing research. 2013;17(4):317–328. | Intervention/exposure
579 | Mazzeo SE, Kelly NR, Thornton L, Parent skills training to enhance weight loss in overweight children: evaluation of NOURISH. Journal article; Conference proceeding. Obesity (Silver Spring, Md). 2011;19:S106. | Intervention/exposure
580 | McArthur LH, Anguiano R, Gross KH. Are household factors putting immigrant Hispanic children at risk of becoming overweight: a community-based study in eastern North Carolina. J Community Health. Oct 2004;29(5):387–404. doi:10.1023/b:johe.0000038654.40121.df.15471421 | Study design; Outcome
581 | McCurdy K, Gorman KS. Measuring family food environments in diverse families with young children. Appetite. Jun 2010;54(3):615–8. doi:10.1016/j.appet.2010.03.004.20227449 | Study design
582 | Mehta UJ, Siega-Riz AM, Herring AH, Adair LS, Bentley ME. Pregravid body mass index is associated with early introduction of complementary foods. J Acad Nutr Diet. Sep 2012; 112(9): 1374–1379. doi:10.1016/i.jand.2012.06.005.22939440 | Intervention/exposure
583 | Melgar-Quiñonez HR, Kaiser LL. Relationship of child-feeding practices to overweight in lowincome Mexican-American preschool-aged children. J Am Diet Assoc. Jul 2004;104(7):1110–9. doi:10.1016/j.jada.2004.04.030.15215770 | Study design
584 | Mellor JM, Rapoport RB, Maliniak D. The impact of child obesity on active parental consent in school-based survey research on healthy eating and physical activity. Eval Rev. Jun 2008;32(3):298–312. doi:10.1177/0193841x07312682.18223127 | Study design; Intervention/exposure
585 | Mennella JA, Papas MA, Reiter AR, Stallings VA, Trabulsi JC. Early rapid weight gain among formula-fed infants: Impact of formula type and maternal feeding styles. Pediatric Obesity. 2019;14(6):N.PAG–N.PAG. doi:10.1111/ijpo.12503. | Age of all participants at intervention/exposure
586 | Meredith-Jones K, Williams S, Taylor R. Agreement between parental perception of child weight status and actual weight status is similar across different ethnic groups in New Zealand. J Prim Health Care. Dec 2016;8(4):316–324. doi:10.1071/hc16002.29530156 | Study design
587 | Messito MJ, Mendelsohn AL, Katzow MW, Scott MA, Vandyousefi S, Gross RS. Prenatal and Pediatric Primary Care-Based Child Obesity Prevention Program: A Randomized Trial. Pediatrics. Oct 2020;146(4)doi:10.1542/peds.2020-0709. | Intervention/exposure
588 | Metallinos-Katsaras E, Must A, Gorman K. A longitudinal study of food insecurity on obesity in preschool children. J Acad Nutr Diet. Dec 2012;112(12):1949–58. doi:10.1016/j.jand.2012.08.031.23174682 | Intervention/exposure
589 | Metwally AM, Sallam SF, Mawla MAA, Promoting weaning practices and growth of Egyptian infants by using communication for behavioral development approach. BMC Pediatr. 2022;22(1):689. Published 2022 Dec 1. doi:10.1186/s12887-022-03741-0 36456920 | Study design; Country
590 | Mihas C, Mariolis A, Manios Y, Evaluation of a nutrition intervention in adolescents of an urban area in Greece: short- and long-term effects of the VYRONAS study. Public Health Nutr. May 2010;13(5):712–9. doi:10.1017/s1368980009991625.19781127 | Intervention/exposure; Outcome
591 | Mihrshahi S, Battistutta D, Magarey A, Daniels LA. Determinants of rapid weight gain during infancy: baseline results from the NOURISH randomised controlled trial. BMC Pediatr. Nov 7 2011;11:99. doi:10.1186/1471-2431-11-99.22054415 | Study design
592 | Millar L, Kremer P, e Silva-Sanigorski A, Reduction in overweight and obesity from a 3-year community-based intervention in Australia: the 'It's Your Move!' project. Obes Rev. Nov 2011;12 Suppl 2:20–8. doi:10.1111/j.1467-789X.2011.00904.x.22008556 | Study design; Intervention/exposure
593 | Miller DP. Associations between the home and school environments and child body mass index. Article. Social Science and Medicine. 2011;72(5):677–684.21227558 | Age of all participants at intervention/exposure
594 | Miller WC, Hering M, Cothran C, Croteau K, Dunlap R. After-school physical activity and eating behaviors of middle school students in relation to adult supervision. J Nutr Educ Behav. Jul-Aug 2012;44(4):326–34. doi:10.1016/j.jneb.2011.08.002.22309738 | Study design
595 | Moens E, Braet C, Vandewalle J. Observation of parental functioning at mealtime using a sibling design. Appetite. 2013;68:132–138. doi:10.1016/j.appet.2013.04.024 23643569 | Study design; Outcome
596 | Moens E, Braet C, Soetens B. Observation of family functioning at mealtime: a comparison between families of children with and without overweight. J Pediatr Psychol. Jan-Feb 2007;32(1):52–63. doi:10.1093/jpepsy/isl011.16801324 | Study design; Outcome
597 | Moens E, Braet C. Predictors of disinhibited eating in children with and without overweight. Behav Res Ther. Jun 2007;45(6):1357–68.. doi:10.1016/j.brat.2006.10.001.17101117 | Study design; Outcome
598 | Moens E, Braet C. Training parents of overweight children in parenting skills: a 12-month evaluation. Behav Cogn Psychother. Jan 2012;40(1):1–18. doi:10.1017/s1352465811000403.21740603 | Intervention/exposure
599 | Monroe-Lord L, Anderson A, Jones BL, Relationship between Family Racial/Ethnic Backgrounds, Parenting Practices and Styles, and Adolescent Eating Behaviors. Int J Environ Res Public Health. Jun 16 2022;19(12)doi:10.3390/ijerph19127388. | Age of all participants at intervention/exposure
600 | Monterrosa EC, Frongillo EA, Neufeld LM, Egan KA, Ramakrishnan U, Rasmussen KM. Maternal pre-pregnancy body mass index is not associated with infant and young child feeding in low-income Mexican children 1–24 months old. Matern Child Nutr. Apr 2015;11(2):215–28. doi:10.1111/j.1740-8709.2012.00461.x.23061488 | Intervention/exposure
601 | Montgomery C, Jackson DM, Kelly LA, Reilly JJ. Parental feeding style, energy intake and weight status in young Scottish children. Br J Nutr. Dec 2006;96(6):1149–53. doi:10.1017/bjn20061968.17181891 | Study design
602 | Montgomery-Reagan K, Bianco JA, Heh V, Rettos J, Huston RS. Prevalence and correlates of high body mass index in rural Appalachian children aged 6–11 years. Rural Remote Health. 2009;9(4):1234.19848443 | Intervention/exposure
603 | Moodie M, Haby M, Wake M, Gold L, Carter R. Cost-effectiveness of a family-based GPmediated intervention targeting overweight and moderately obese children. Journal article. Economics and human biology. 2008;6(3):363–376. doi:10.1016/j.ehb.2008.06.001.18657487 | Intervention/exposure
604 | Moore SM, Borawski EA, Love TE, Two Family Interventions to Reduce BMI in LowIncome Urban Youth: A Randomized Trial. Pediatrics. 2019;143(6):e20182185. doi:10.1542/peds.2018-2185 31126971 | Intervention/exposure
605 | Moraes AC, Falcão MC. Lifestyle factors and socioeconomic variables associated with abdominal obesity in Brazilian adolescents. Ann Hum Biol. Jan 2013;40(1):1–8. doi:10.3109/03014460.2012.745900.23301800 | Intervention/exposure
606 | Morandi A, Tommasi M, Fornari E, Tomasselli F, Maffeis C. Prevention of obesity in toddlers: the PROBIT trial. Journal article; Conference proceeding. Obesity facts. 2018;11:58–59. | Intervention/exposure; Comparator
607 | Morandi A, Tommasi M, Soffiati F, Prevention of obesity in toddlers (PROBIT): a randomised clinical trial of responsive feeding promotion from birth to 24 months. Article. International Journal of Obesity. 2019;43(10):1961–1966.. doi:10.1038/s41366-019-0406-0.31270429 | Intervention/exposure
608 | Morano M, Rutigliano I, Rago A, Pettoello-Mantovani M, Campanozzi A. A multicomponent, school-initiated obesity intervention to promote healthy lifestyles in children. Nutrition. Oct 2016;32(10):1075–80. doi:10.1016/j.nut.2016.03.007.27209213 | Intervention/exposure
609 | Moreira I, Severo M, Oliveira A, Social and health behavioural determinants of maternal child-feeding patterns in preschool-aged children. Matern Child Nutr. Apr 2016;12(2):314–25. doi:10.1111/mcn.12132.24697990 | Study design
610 | Moreno JP, Kelley ML, Landry DN, Development and validation of the Family Health Behavior Scale. Int J Pediatr Obes. Jun 2011;6(2–2):e480–6. doi:10.3109/17477166.2011.575148.21615229 | Study design
611 | Morgan PJ, Collins CE, Plotnikoff RC, The 'Healthy Dads, Healthy Kids' community randomized controlled trial: a community-based healthy lifestyle program for fathers and their children. Prev Med. Apr 2014;61:90–9.. doi:10.1016/j.ypmed.2013.12.019.24380796 | Intervention/exposure
612 | Mori S, Asakura K, Sasaki S, Nishiwaki Y. Relationship between maternal employment status and children's food intake in Japan. Environ Health Prev Med. Oct 28 2021;26(1):106. doi:10.1186/s12199-021-01026-z.34711169 | Study design; Outcome
613 | Morin KH. Parental style of infant and child feeding: how influential is it? MCN Am J Matern Child Nurs. Nov-Dec 2006;31(6):388. doi:10.1097/00005721-200611000-00011.17149116 | Study design; Publication status
614 | Morrison H, Power TG, Nicklas T, Hughes SO. Exploring the effects of maternal eating patterns on maternal feeding and child eating. Appetite. Apr 2013;63:77–83. doi:10.1016/j.appet.2012.12.017.23291285 | Study design; Outcome
615 | Morrissey TW. Maternal depressive symptoms and weight-related parenting behaviors. Matern Child Health J. Aug 2014;18(6):1328–35. doi:10.1007/s10995-013-1366-y.24077962 | Intervention/exposure; Outcome
616 | Morshed AB, Tabak RG, Schwarz CD, Haire-Joshu D. The Impact of a Healthy Weight Intervention Embedded in a Home-Visiting Program on Children's Weight and Mothers' Feeding Practices. J Nutr Educ Behav. Feb 2019;51(2):237–244. doi:10.1016/j.jneb.2018.09.001.30385250 | Intervention/exposure; Outcome
617 | Mosli RH, Miller AL, Peterson KE, Lumeng JC. Sibling feeding behavior: Mothers as role models during mealtimes. Appetite. Jan 1 2016;96:617–620. doi:10.1016/j.appet.2015.11.006.26585632 | Study design; Outcome
618 | Mosli RH. The association between sibship composition and maternal feeding behaviors. Article. Progress in Nutrition. 2021;23(3) | Study design; Intervention/exposure; Outcome
619 | Mrdjenovic G, Levitsky DA. Children eat what they are served: the imprecise regulation of energy intake. Appetite. Jun 2005;44(3):273–82. doi:10.1016/j.appet.2005.01.005.15927729 | Intervention/exposure; Outcome
620 | Mulder C, Kain J, Uauy R, Seidell JC. Maternal attitudes and child-feeding practices: relationship with the BMI of Chilean children. Nutr J. Aug 13 2009;8:37. doi:10.1186/1475-28918-37.19678925 | Study design; Intervention/exposure; Outcome
621 | Munkholm A, Olsen EM, Rask CU, Early Predictors of Eating Problems in Preadolescence-A Prospective Birth Cohort Study. J Adolesc Health. May 2016;58(5):533–42. doi:10.1016/j.jadohealth.2016.01.006.27107908 | Intervention/exposure
622 | Murashima M, Hoerr SL, Hughes SO, Kattelmann KK, Phillips BW. Maternal parenting behaviors during childhood relate to weight status and fruit and vegetable intake of college students. J Nutr Educ Behav. Nov-Dec 2012;44(6):556–63. doi:10.1016/j.jneb.2011.05.008.22137501 | Study design
623 | Murdoch M, Payne N, Samani-Radia D, Family-based behavioural management of childhood obesity: service evaluation of a group programme run in a community setting in the United Kingdom. Eur J Clin Nutr. Jun 2011;65(6):764–7. doi:10.1038/ejcn.2011.23.21427740 | Study design; Intervention/exposure
624 | Murillo R, Pirzada A, Wu D, The Association Between Family Social Network Size and Healthy Lifestyle Factors: Results from the Hispanic Community Health Study/Study of Latinos (HCHS/SOL). J Behav Med. Apr 2020;43(2):198–208. doi:10.1007/s10865-019-00082-9.31350713 | Study design
625 | Musaad SM, Donovan SM, Fiese BH. Parental perception of child weight in the first two yearsof-life: a potential link between infant feeding and preschoolers' diet. Appetite. Aug 2015;91:90 100. doi:10.1016/j.appet.2015.03.029.25843938 | Intervention/exposure; Outcome
626 | Musher-Eizenman DR, e Lauzon-Guillain B, Holub SC, Leporc E, Charles MA. Child and parent characteristics related to parental feeding practices. A cross-cultural examination in the US and France. Appetite. Feb 2009;52(1):89–95. doi:10.1016/j.appet.2008.08.007.18789986 | Study design
627 | Mushquash AR, Rasquinha AM, Friedman A, Ball GDC. Examining the Accuracy and Use of Portion Size Estimation Aids in Parents of Children With Obesity: A Randomized Controlled Trial. J Nutr Educ Behav. Oct 2018;50(9):918–923.doi:10.1016/j.jneb.2018.06.005.30297017 | Intervention/exposure; Outcome
628 | Mustila T, Raitanen J, Keskinen P, Luoto R. A pragmatic controlled trial to prevent childhood obesity within a risk group at maternity and child health-care clinics: results up to six years of age (the VACOPP study). BMC Pediatr. Feb 27 2018;18(1):89. doi:10.1186/s12887-018-1065-3.29486763 | Intervention/exposure
629 | Nafista UF, Nurhaeni N, Waluyanti FT. Improvement in maternal knowledge, attitudes, and children's weight with education on World Health Organization feeding recommendations. Pediatr Med Chir. Mar 28 2023;45(s1)doi:10.4081/pmc.2023.314. | Intervention/exposure
630 | Nagao-Sato S, Davila SAd, Popelka JM, Feasibility of a remotely delivered program to prevent Latino adolescent obesity in the Midwestern USA. Health Promotion International. 2022;37(4):1–11. doi:10.1093/heapro/daac106. | Intervention/exposure; Outcome
631 | Natale R, Atem FD, Lebron C, Cluster-randomised trial of the impact of an obesity prevention intervention on childcare centre nutrition and physical activity environment over 2 years. Journal article. Public health nutrition. 2022;25(11):3172–3181. doi:10.1017/S1368980021004109.34593076 | Intervention/exposure
632 | Neumark-Sztainer D, Bauer KW, Friend S, Hannan PJ, Story M, Berge JM. Family weight talk and dieting: how much do they matter for body dissatisfaction and disordered eating behaviors in adolescent girls? J Adolesc Health. Sep 2010;47(3):270–6. doi:10.1016/j.jadohealth.2010.02.001.20708566 | Study design
633 | Neumark-Sztainer D, Eisenberg ME, Fulkerson JA, Story M, Larson NI. Family meals and disordered eating in adolescents: longitudinal findings from project EAT. Arch Pediatr Adolesc Med. Jan 2008;162(1):17–22. doi:10.1001/archpediatrics.2007.9.18180407 | Outcome
634 | Neumark-Sztainer D, Wall M, Story M, Sherwood NE. Five-year longitudinal predictive factors for disordered eating in a population-based sample of overweight adolescents: implications for prevention and treatment. Int J Eat Disord. Nov 2009;42(7):664–72. doi:10.1002/eat.20733.19642214 | Intervention/exposure; Outcome
635 | Neumark-Sztainer DR, Wall MM, Haines JI, Story MT, Sherwood NE, van den Berg PA. Shared risk and protective factors for overweight and disordered eating in adolescents. Am J Prev Med. Nov 2007;33(5):359–369.. doi:10.1016/j.amepre.2007.07.031.17950400 | Age of all participants at intervention/exposure
636 | Nguyen ND, Allen JR, Peat JK, Growth and feeding practices of Vietnamese infants in Australia. Eur J Clin Nutr. 2004;58(2):356–362. doi:10.1038/sj.ejcn.1601791 14749758 | Intervention/exposure
637 | Nix RL, Francis LA, Feinberg ME, Improving Toddlers' Healthy Eating Habits and Selfregulation: A Randomized Controlled Trial. Pediatrics. Jan 2021; 147(1). doi:10.1542/peds.20193326. | Intervention/exposure; Outcome
638 | Njardvik U, Klar EK, Thorsdottir F. The factor structure of the Children's Eating Behaviour Questionnaire: A comparison of four models using confirmatory factor analysis. Health Sci Rep. Mar 2018;1(3):e28. doi:10.1002/hsr2.28.30623064 | Study design; Outcome
639 | Noor AM, Leelavathi M, Shamsul AS, Hizlinda T, Khairani O, Fatimah A. Parental concerns and control in feeding of 9 to 12-year-old children in a primary school in Kuala Lumpur, Malaysia. Malays J Nutr. 2012;18(1):47–55.23713229 | Study design
640 | Nowicka P, Sorjonen K, Pietrobelli A, Flodmark CE, Faith MS. Parental feeding practices and associations with child weight status. Swedish validation of the Child Feeding Questionnaire finds parents of 4-year-olds less restrictive. Appetite. 2014;81:232–241. doi:10.1016/j.appet.2014.06.027 24972134 | Study design
641 | Nsiah-Kumi PA, Ariza AJ, Mikhail LM, Feinglass J, Binns HJ. Family history and parents' beliefs about consequences of childhood overweight and their influence on children's health behaviors. Acad Pediatr. Jan-Feb 2009;9(1):53–9. doi:10.1016/j.acap.2008.11.001.19329092 | Study design; Intervention/exposure
642 | Nuss K, Coulter R, DeSilva B, Evaluating the Effectiveness of a Family-Based Virtual Childhood Obesity Management Program Delivered During the COVID-19 Pandemic in Canada: Prospective Study. JMIR Pediatr Parent. Nov 3 2022;5(4):e40431. doi:10.2196/40431.36054663 | Intervention/exposure; Outcome
643 | Nuvoli G. Family meal frequency, weight status and healthy management in children, young adults and seniors. A study in Sardinia, Italy. Appetite. Jun 2015;89:160–6. doi:10.1016/j.appet.2015.02.007.25681295 | Study design
644 | Nyberg G, Sundblom E. Effectiveness of a universal parental support programme to promote healthy dietary habits and physical activity and to prevent overweight and obesity in 6-year-old children: the Healthy School Start Study, a cluster-randomised controlled trial. PLoS One. 2015;10(2):e0116876. doi:10.1371/iournal.pone.0116876.25680096 | Intervention/exposure; Outcome
645 | O'Brien M, Nader PR, Houts RM, The ecology of childhood overweight: a 12-year longitudinal analysis. Int J Obes (Lond). Sep 2007;31(9):1469–78. doi:10.1038/sj.ijo.0803611.17406272 | Intervention/exposure
646 | Ochoa MC, Moreno-Aliaga MJ, Martínez-González MA, Martínez JA, Marti A. Predictor factors for childhood obesity in a Spanish case-control study. Nutrition. May 2007;23(5):379–84. doi:10.1016/j.nut.2007.02.004.17408922 | Study design; Intervention/exposure
647 | O'Connor TM, Hilmers A, Watson K, Baranowski T, Giardino AP. Feasibility of an obesity intervention for paediatric primary care targeting parenting and children: Helping HAND. Child Care Health Dev. Jan 2013;39(1):141–9. doi:10.1111/j.1365-2214.2011.01344.x.22066521 | Intervention/exposure
648 | Odar Stough C, Bolling C, Zion C, Stark LJ. Comparison of High and Normal Birth Weight Infants on Eating, Feeding Practices, and Subsequent Weight. Matern Child Health J. Dec 2018;22(12):1805–1814. doi:10.1007/s10995-018-2581-3.30008043 | Study design
649 | Ogden J, Cordey P, Cutler L, Thomas H. Parental restriction and children's diets. The chocolate coin and Easter egg experiments. Appetite. Feb 2013;61(1):36–44. doi:10.1016/j.appet.2012.10.021.23142562 | Outcome
650 | Okely AD, Collins CE, Morgan PJ, Multi-site randomized controlled trial of a child-centered physical activity program, a parent-centered dietary-modification program, or both in overweight children: the HIKCUPS study. J Pediatr. Sep 2010;157(3):388–94, 394.e1. doi:10.1016/j.jpeds.2010.03.028.20447648 | Intervention/exposure
651 | Olfert MD, Barr ML, Hagedorn RL, Health Disparities Score Composite of Youth and Parent Dyads from an Obesity Prevention Intervention: iCook 4-H. Healthcare (Basel). May 22 2018;6(2)doi:10.3390/healthcare6020051. | Intervention/exposure
652 | Olvera N, Bush JA, Sharma SV, Knox BB, Scherer RL, Butte NF. BOUNCE: a community-based mother-daughter healthy lifestyle intervention for low-income Latino families. Obesity (Silver Spring). Feb 2010;18 Suppl 1:S102–4. doi:10.1038/oby.2009.439.20107454 | Intervention/exposure
653 | Olvera N, Power TG. Brief report: parenting styles and obesity in Mexican American children: a longitudinal study. J Pediatr Psychol. Apr 2010;35(3):243–9. doi:10.1093/jpepsy/jsp071.19726552 | Study design; Intervention/exposure
654 | Ontai LL, Sutter C, Sitnick S, Shilts MK, Townsend MS. Parent Food-Related Behaviors and Family-Based Dietary and Activity Environments: Associations with BMI z-Scores in Low-Income Preschoolers. Childhood Obesity. 2020;16:S-55–S-63. doi:10.1089/chi.2019.0105.33253009 | Study design; Intervention/exposure
655 | Orün E, Erdil Z, Cetinkaya S, Tufan N, Yalçin SS. Problematic eating behaviour in Turkish children aged 12–72 months: characteristics of mothers and children. Cent Eur J Public Health. Dec 2012;20(4):257–61. doi:10.21101/cejph.a3748.23441389 | Study design; Intervention/exposure
656 | Østbye T, Lyna P, Bodner ME, The effect of parental presence on weight-related discussions between physicians and their overweight adolescent patients. Article. Clinical Pediatrics. 2015;54(12):1218–1219. doi:10.1177/0009922814566027.25575503 | Study design; Outcome
657 | Østbye T, Malhotra R, Stroo M, The effect of the home environment on physical activity and dietary intake in preschool children. Int J Obes (Lond). Oct 2013;37(10):1314–21. doi:10.1038/ijo.2013.76.23736357 | Study design
658 | Quattrin T, Roemmich JN, Paluch R, Yu J, Epstein LH, Ecker MA. Efficacy of family-based weight control program for preschool children in primary care. Pediatrics. 2012;130(4):660–666. doi:10.1542/peds.2012-0701 22987879 | Intervention/exposure
659 | Overcash FM, Vickers Z, Ritter AE, An in-home intervention of parent-implemented strategies to increase child vegetable intake: results from a non-randomized cluster-allocated community trial. BMC Public Health. Jul 4 2019;19(1):881. doi:10.1186/s12889-019-7079-4.31272404 | Intervention/exposure; Outcome
660 | Pai HL, Contento I. Parental perceptions, feeding practices, feeding styles, and level of acculturation of Chinese Americans in relation to their school-age child's weight status. Appetite. 2014;80:174–182. doi:10.1016/j.appet.2014.04.029 24816322 | Study design
661 | Palacios C, Campos M, Gibby C, Melendez M, Lee JE, Banna J. Effect of a Multi-Site Trial using Short Message Service (SMS) on Infant Feeding Practices and Weight Gain in Low-Income Minorities. J Am Coll Nutr. Sep-Oct 2018;37(7):605–613. doi:10.1080/07315724.2018.1454353.29708471 | Intervention/exposure
662 | Palfreyman Z, Haycraft E, Meyer C. Parental modelling of eating behaviours: observational validation of the Parental Modelling of Eating Behaviours scale (PARM). Appetite. Mar 2015;86:31–7. doi:10.1016/j.appet.2014.08.008.25111293 | Study design; Outcome
663 | Palfreyman Z, Haycraft E, Meyer C. Development of the Parental Modelling of Eating Behaviours Scale (PARM): links with food intake among children and their mothers. Matern Child Nutr. 2014;10(4):617–629. doi:10.1111/j.1740-8709.2012.00438.x 22906242 | Study design; Publication status
664 | Panagiotopoulos C, Ronsley R, Al-Dubayee M, The Centre for Healthy Weights-Shapedown BC: a family-centered, multidisciplinary program that reduces weight gain in obese children over the short-term. Journal article. International journal of environmental research and public health. 2011;8(12):4662–4678.22408595 | Study design; Intervention/exposure
665 | Papaioannou MA, Micheli N, Power TG, O'Connor TM, Fisher JO, Hughes SO. Maternal Feeding Styles and Child Appetitive Traits: Direction of Effects in Hispanic Families With Low Incomes. Front Public Health. 2022;10:871923. Published 2022 Jun 2. doi:10.3389/fpubh.2022.871923 35719648 | Outcome
666 | Papaioannou MA, Cross MB, Power TG, Feeding style differences in food parenting practices associated with fruit and vegetable intake in children from low-income families. J Nut Educ Behav. Nov-Dec 2013;45(6):643–51. doi:10.1016/j.jneb.2013.05.007. | Study design; Outcome
667 | Parkes A, Green M, Pearce A. Do bedroom screens and the mealtime environment shape different trajectories of child overweight and obesity? Research using the Growing Up in Scotland study. Int J Obes (Lond). Apr 2020;44(4):790–802. doi:10.1038/s41366-019-0502-1.31827254 | Intervention/exposure;
668 | Parkinson KN, Wright CM, Drewett RF. Mealtime energy intake and feeding behaviour in children who fail to thrive: a population-based case-control study. J Child Psychol Psychiatry. 2004;45(5):1030–5doi:10.1111/j.1469-7610.2004.t01–1-00294.x.15225344 | Outcome
669 | Patel N, Dalrymple KV, Briley AL, Mode of infant feeding, eating behaviour and anthropometry in infants at 6-months of age born to obese women - a secondary analysis of t UPBEAT trial. BMC Pregnancy Childbirth. Sep 3 2018;18(1):355. doi:10.1186/s12884-018-1995-7.30176807 | Intervention/exposure
670 | Patrick H, Nicklas TA, Hughes SO, Morales M. The benefits of authoritative feeding style: caregiver feeding styles and children's food consumption patterns. Appetite. Apr 2005;44(2):243–9. doi:10.1016/j.appet.2002.07.001.15808898 | Study design; Outcome
671 | Patsopoulou A, Tsimtsiou Z, Katsioulis A, Rachiotis G, Malissiova E, Hadjichristodoulou C. Prevalence and Risk Factors of Overweight and Obesity among Adolescents and Their Parent in Central Greece (FETA Project). Int J Environ Res Public Health. Dec 26 2015;13(1):83. doi:10.3390/ijerph13010083.26712779 | Study design
672 | Paul IM, Savage JS, Anzman SL, Preventing obesity during infancy: a pilot study. Obesi (Silver Spring). Feb 2011;19(2):353–61. doi:10.1038/oby.2010.182. | Age of all participants at intervention/exposure
673 | Paul IM, Savage JS, Anzman-Frasca S, Effect of a Responsive Parenting Educational Intervention on Childhood Weight Outcomes at 3 Years of Age: The INSIGHT Randomized Clinical Trial. Jama. Aug 7 2018;320(5):461–468. doi:10.1001/jama.2018.9432.30088009 | Study design; Intervention/exposure
674 | Pbert L, Druker S, Barton B, Use of a FITLINE to Support Families of Overweight and Obese Children in Pediatric Practices. Child Obes. Feb 2016;12(1):33–43. doi:10.1089/chi.2015.0101.26788762 | Intervention/exposure
675 | Pengpid S, Peltzer K. Overweight and Obesity and Associated Factors among School-Aged Adolescents in Six Pacific Island Countries in Oceania. Int J Environ Res Public Health. Nov 13 2015;12(11):14505–18. doi:10.3390/ijerph121114505.26580638 | Study design; Intervention/exposure
676 | Penilla C, Tschann JM, Deardorff J, Fathers' feeding practices and children's weight status in Mexican American families. Appetite. Oct 1 2017;117:109–116. doi:10.1016/j.appet.2017.06.016.28629931 | Study design; Age of all participants at intervention/exposure
677 | Perrin EM, Jacobson Vann JC, Benjamin JT, Skinner AC, Wegner S, Ammerman AS. Use of pediatrician toolkit to address parental perception of children's weight status, nutrition, and activity behaviors. Acad Pediatr. Jul-Aug 2010;10(4):274–81.. doi:10.1016/j.acap.2010.03.006.20554259 | Study design; Intervention/exposure
678 | Perrin EM, Rothman RL, Sanders LM, Racial and ethnic differences associated with feeding- and activity-related behaviors in infants. Pediatrics. Apr 2014;133(4):e857–67. doi:10.1542/peds.2013-1326.24639273 | Study design
679 | Pesch MH, Appugliese DP, Kaciroti N, Rosenblum KL, Miller AL, Lumeng JC. Maternal encouragement and discouragement: Differences by food type and child weight status. Appet Jun 1 2016;101:15–22. doi:10.1016/j.appet.2016.02.146. | Study design
680 | Pesch MH, Miller AL, Appugliese DP, Kaciroti N, Rosenblum KL, Lumeng JC. Low-income mothers' feeding goals predict observed home mealtime and child feeding practices. Child Care Health Dev. Nov 2016;42(6):934–940. doi:10.1111/cch.12396.27558923 | Study design; Outcome
681 | Pesch MH, Miller AL, Appugliese DP, Rosenblum KL, Lumeng JC. Affective tone of mothers' statements to restrict their children's eating. Appetite. Aug 1 2016;103:165–170. doi:10.1016/j.appet.2016.04.015.27090342 | Study design; Outcome
682 | Petrauskiene A, Dregval L, Petkute S. Health behavior of families having preschool-age children. Article. Medicina (Kaunas, Lithuania). 2007;43(10):816–823. doi:10.3390/medicina43100105.17998800 | Study design; Intervention/exposure
683 | Pham TTP, Matsushita Y, Dinh LTK, Prevalence and associated factors of overweight and obesity among schoolchildren in Hanoi, Vietnam. BMC Public Health. Nov 8 2019;19(1):1478. doi:10.1186/s12889-019-7823-9.31703653 | Study design
684 | Piazza-Waggoner C, Modi AC, Ingerski LM, Wu YP, Zeller MH. Distress at the Dinner Table? Observed Mealtime Interactions among Treatment-Seeking Families of Obese Children. Child Obes. Oct 18 2011;7(5):385–391. doi:10.1089/chi.2011.0066.23275861 | Study design; Outcome
685 | Pinard CA, Yaroch AL, Hart MH, Serrano EL, McFerren MM, Estabrooks PA. The Validity and reliability of the Comprehensive Home Environment Survey (CHES). Health Promot Pract. Jan 2014;15(1):109–17. doi:10.1177/1524839913477863.23471699 | Study design; Outcome
686 | Pinard C, Byker C, Harden S, Influences on Food Away from Home Feeding Practices Among English and Spanish Speaking Parent-Child Dyads. Journal of Child & Family Studies. 2015;24(7):2099–2106. | Study design
687 | Pinket AS, De Craemer M, Huybrechts I, Multibehavioural Interventions with a Focus on Specific Energy Balance-Related Behaviours Can Affect Diet Quality in Preschoolers from Six European Countries: The ToyBox-Study. Nutrients. May 10 2017;9(5)doi:10.3390/nu9050479. | Intervention/exposure; Outcome
688 | Polat S, Erci B. Psychometric properties of the child feeding scale in Turkish mothers. Asian Nurs Res (Korean Soc Nurs Sci). Sep 2010;4(3):111–21. doi:10.1016/s1976-1317(10)60011-4.25031092 | Study design
689 | Polfuss ML, Frenn M. Parenting and feeding behaviors associated with school-aged African American and White children. West J Nurs Res. Aug 2012;34(5):677–96. doi:10.1177/0193945911402225.21427450 | Study design
690 | Porter JS, Bean MK, Gerke CK, Stern M. Psychosocial factors and perspectives on weight gain and barriers to weight loss among adolescents enrolled in obesity treatment. J Clin Psychol Med Settings. Jun 2010;17(2):98–102. doi:10.1007/s10880-010-9186-3.20119710 | Study design; Intervention/exposure; Outcome
691 | Power TG, Hughes SO, Goodell LS, Feeding practices of low-income mothers: how do they compare to current recommendations? Int J Behav Nutr Phys Act. Mar 7 2015;12:34. doi:10.1186/s12966-015-0179-3.25888909 | Study design; Outcome
692 | Power TG, O'Connor TM, Orlet Fisher J, Hughes SO. Obesity Risk in Children: The Role of Acculturation in the Feeding Practices and Styles of Low-Income Hispanic Families. Child Obes. Dec 2015;11(6):715–21. doi:10.1089/chi.2015.0036.26584157 | Study design; Outcome
693 | Power TG, Silva Garcia K, Beck AD, Goodell LS, Johnson SL, Hughes SO. Observed and self-reported assessments of caregivers' feeding styles: Variable- and person-centered approaches for examining relationships with children's eating behaviors. Appetite. Nov 1 2018;130:174–183. doi:10.1016/j.appet.2018.08.010.30099067 | Study design
694 | Powers SW, Chamberlin LA, van Schaick KB, Sherman SN, Whitaker RC. Maternal feeding strategies, child eating behaviors, and child BMI in low-income African-American preschoolers. Obesity (Silver Spring). Nov 2006;14(11):2026–33. doi:10.1038/oby.2006.237.17135620 | Study design
695 | Prado G, Fernandez A, St George SM, Results of a Family-Based Intervention Promoting Healthy Weight Strategies in Overweight Hispanic Adolescents and Parents: An RCT. Am J Prev Med. Nov 2020;59(5):658–668. doi:10.1016/j.amepre.2020.06.010.33011010 | Intervention/exposure
696 | Pratt KJ, Ferriby M, Brown CL, Noria S, Needleman B, Skelton JA. Adult weight management patients' perceptions of family dynamics and weight status. Clin Obes. Oct 2019;9(5):e12326. doi:10.1111/cob.12326.31232524 | Intervention/exposure; Outcome
697 | Pridham KF, Brown R, Clark R, Sondel S, Green C. Infant and caregiving factors affecting weight-for-age and motor development of full-term and premature infants at 1 year post-term. Res Nurs Health. Oct 2002;25(5):394–410. doi:10.1002/nur.10047.12221693 | Intervention/exposure
698 | Pryor LE, Brendgen M, Tremblay RE, Early Risk Factors of Overweight Developmental Trajectories during Middle Childhood. PLoS One. 2015;10(6):e0131231. doi:10.1371/journal.pone.0131231.26121682 | Intervention/exposure
699 | Puhl RM, Schwartz MB. If you are good you can have a cookie: How memories of childhood food rules link to adult eating behaviors. Eat Behav. Sep 2003;4(3):283–93. doi:10.1016/s1471-0153(03)00024-2.15000971 | Study design
700 | Pulley C, Galloway AT, Webb RM, Payne LO. Parental child feeding practices: how do perceptions of mother, father, sibling, and self vary? Appetite. Sep 2014;80:96–102. doi:10.1016/j.appet.2014.05.001.24819343 | Study design
701 | Queiroz VADO, Assis AMO, Pinheiro SMC, Ribeiro Jr HDC. Predictors of linear growth in the first year of life of a prospective cohort of full term children with normal birth weight. Article. Jornal de Pediatria. 2012;88(1):79–86. doi:10.2223/JPED.2143.22344528 | Intervention/exposure
702 | Quelly SB, Eckhoff DO, Luzincourt G, Garcia J, Smith S. Feasibility of parents promoting fruit-infused water to reduce preschool children's sugar-sweetened beverage consumption. Article. Nutrition and health. 2022;28(3):291–296. doi:10.1177/02601060221086113.35289221 | Intervention/exposure; Outcome
703 | Quick V, Wall M, Larson N, Haines J, Neumark-Sztainer D. Personal, behavioral and socio-environmental predictors of overweight incidence in young adults: 10-yr longitudinal findings. Int J Behav Nutr Phys Act. Mar 25 2013;10:37. doi:10.1186/1479-5868-10-37.23531253 | Age of all participants at intervention/exposure
704 | R EY, Tombeg Z, Hadi AJ, Manggabarani S. The Effect of Family-Based Empowerment on Adolescent's Nutritional Status in Tana Toraja. Medico-Legal Update. 2021;21(2):501–506. | Intervention/exposure
705 | Ranjit N, Wilkinson AV, Lytle LM, Evans AE, Saxton D, Hoelscher DM. Socioeconomic inequalities in children's diet: the role of the home food environment. Int J Behav Nutr Phys Act. Jul 27 2015;12 Suppl 1(Suppl 1):S4. doi:10.1186/1479-5868-12-s1-s4.26222785 | Study design
706 | Raychaudhuri M, Sanyal D. Childhood obesity: Determinants, evaluation, and prevention. Indian J Endocrinol Metab. Dec 2012;16(Suppl 2):S192–4. doi:10.4103/2230-8210.104037.23565376 | Publication status
707 | Raynor HA, Propst S, Robson S, Berlin KS, Barroso CS, Khatri P. Implementing Prevention Plus with Underserved Families in an Integrated Primary Care Setting. Article. Childhood obesity (Print). 2022;18(4):254–265. doi:10.1089/chi.2021.0071.34767729 | Intervention/exposure
708 | Reed M, Julion W, McNaughton D, Wilbur J. Preferred intervention strategies to improve dietary and physical activity behaviors among African-American mothers and daughters. Public Health Nurs. Sep 2017;34(5):461–471. doi:10.1111/phn.12339.28639382 | Study design
709 | Reifsnider E, Shin CN, Todd M, Jeong M, Gallagher M, Moramarco M. How Did They Grow: An Intervention to Reduce Stunted Growth in Low-Income Mexican-American Children. Res Nurs Health. 2016;39(2):105–120. doi:10.1002/nur.21714 26915468 | Intervention/exposure
710 | Reina SA, Shomaker LB, Mooreville M, Sociocultural pressures and adolescent eating in the absence of hunger. Body Image. Mar 2013;10(2):182–90. doi:10.1016/j.bodyim.2012.12.004.23394966 | Study design; Outcome
711 | Reinehr T, Brylak K, Alexy U, Kersting M, Andler W. Predictors to success in outpatient training in obese children and adolescents. Int J Obes Relat Metab Disord. Sep 2003;27(9):1087–92. doi:10.1038/sj.ijo.0802368.12917715 | Study design; Intervention/exposure
712 | Rempel JK, Rempel LA, Hoa DTP, Vui LT, Long TK. Parenting Teamwork: The Impact of a Fathering Intervention on Mothers and Infants in Vietnam. Article. Child development. 2020;91(2):e345–e364. doi:10.1111/cdev.13244.30937897 | Intervention/exposure
713 | Retzloff L, Lumeng JC, Kaciroti N, Rosenblum K, Miller AL. Longitudinal associations between maternal feeding and overweight in low-income toddlers. Appetite. 2017:23–29. doi:10.1016/j.appet.2017.02.016. | Age of all participants at intervention/exposure
714 | Reynolds LAF, McCaffery H, Appugliese D, Capacity for Regulation of Energy Intake in Infancy. JAMA Pediatr. Jun 1 2023;177(6):590–598. doi:10.1001/jamapediatrics.2023.0688.37067796 | Outcome
715 | Rhee KE, Boutelle KN, Jelalian E, Barnes R, Dickstein S, Wing RR. Firm maternal parenting associated with decreased risk of excessive snacking in overweight children. Eat Weight Disord. Jun 2015;20(2):195–203. doi:10.1007/s40519-014-0164-x.25370704 | Study design; Outcome
716 | Rhee KE, Jelalian E, Boutelle K, Dickstein S, Seifer R, Wing R. Warm Parenting Associated with Decreasing or Stable Child BMI during Treatment. Child Obes. Apr 2016;12(2):94–102. doi:10.1089/chi.2015.0127.26895374 | Intervention/exposure
717 | Rhee KE, Manzano M, Goffin S, Strong D, Boutelle KN. Exploring the relationship between appetitive behaviours, executive function, and weight status among preschool children. Pediatr Obes. Aug 2021;16(8):e12774. doi:10.1111/ijpo.12774.33530135 | Study design; Intervention/exposure
718 | Rhee KE, Pan TY, Norman GJ, Crow S, Boutelle K. Relationship between maternal parenting and eating self-efficacy in overweight children when stressed. Eat Weight Disord. Sep 2013;18(3):283–8. doi:10.1007/s40519-013-0043-x.23868554 | Study design
719 | Ricci CL, Brown BD, Noonan C, Parental influence on obesity in Northern Plains American Indian youth. Fam Community Health. Jan-Mar 2012;35(1):68–75. doi:10.1097/FCH.0b013e3182385d64.22143489 | Study design
720 | Richards R, Smith C, Eggett DL. Correlates of energy intake and body mass index among homeless children in Minnesota. Child Obes. Jun 2013;9(3):240–51. doi:10.1089/chi.2012.0026.23705886 | Study design
721 | Riesch SK, Lyles A, Perez O, Brown RL, Kotula K, Sass-Deruyter SM. Modifiable family factors among treatment-seeking families of children with high body mass index: report of a pilot study. J Pediatr Health Care. Jul-Aug 2013;27(4):254–66. doi:10.1016/j.pedhc.2011.11.006.22226736 | Study design
722 | Rifas-Shiman SL, Sherry B, Scanlon K, Birch LL, Gillman MW, Taveras EM. Does maternal feeding restriction lead to childhood obesity in a prospective cohort study? Arch Dis Child. Mar 2011;96(3):265–9. doi:10.1136/adc.2009.175240.21081589 | Age of all participants at intervention/exposure
723 | Rios-Castillo I, Cerezo S, Corvalán C, Martínez M, Kain J. Risk factors during the prenatal period and the first year of life associated with overweight in 7-year-old low-income Chilean children. Matern Child Nutr. Oct 2015;11(4):595–605. doi:10.1111/mcn.12024.23241511 | Intervention/exposure
724 | Rito AI, Carvalho MA, Ramos C, Breda J. Program Obesity Zero (POZ)--a community-based intervention to address overweight primary-school children from five Portuguese municipalities. Public Health Nutr. Jun 2013;16(6):1043–51. doi:10.1017/s1368980013000244.23462320 | Intervention/exposure
725 | Roach, E, Viechnicki, GB, Retzloff, LB, Davis-Kean, P, Lumeng, JC, Miller, AL. Roach E, Viechnicki GB, Retzloff LB, Davis-Kean P, Lumeng JC, Miller AL. Family food talk, child eating behavior, and maternal feeding practices. Appetite. Oct 1 2017;117:40–50. doi:10.1016/j.appet.2017.06.001.28587941 | Study design
726 | Roberts LT, Carbonneau N, Goodman LC, Musher-Eizenman DR. Retrospective reports of childhood feeding in mother-daughter dyads. Appetite. Jun 1 2020;149:104613. doi:10.1016/j.appet.2020.104613.31987877 | Age of all participants at intervention/exposure
727 | Robertson J, Puckering C, Parkinson K, Corlett L, Wright C. Mother-child feeding interactions in children with and without weight faltering; nested case control study. Appetite. Jun 2011;56(3):753–9.. doi:10.1016/j.appet.2011.02.016.21396417 | Outcome; Health status
728 | Robertson W, Fleming J, Kamal A, Randomised controlled trial evaluating the effectiveness and cost-effectiveness of'Families for Health', a family-based childhood obesity treatment intervention delivered in a community setting for ages 6 to 11 years. Health Technol Assess. Jan 2017;21(1):1–180.doi:10.3310/hta21010. | Age of all participants at intervention/exposure
729 | Robertson W, Friede T, Blissett J, Rudolf MC, Wallis M, Stewart-Brown S. Pilot of "Families for Health": community-based family intervention for obesity. Arch Dis Child. Nov 2008;93(11):921 6. doi:10.1136/adc.2008.139162.18463121 | Study design; Intervention/exposure
730 | Robertson W, Thorogood M, Inglis N, Grainger C, Stewart-Brown S. Two-year follow-up of the 'Families for Health' programme for the treatment of childhood obesity. Child Care Health Dev. Mar 2012;38(2):229–36. doi:10.1111/i.1365-2214.2011.01237.x.21463350 | Study design; Intervention/exposure
731 | Robinson TN, Kiernan M, Matheson DM, Haydel KF. Is parental control over children's eating associated with childhood obesity? Results from a population-based sample of third graders. Obes Res. May 2001;9(5):306–12. doi:10.1038/oby.2000.38.11346672 | Study design
732 | Robinson WR, Stevens J, Kaufman JS, Gordon-Larsen P. The role of adolescent behaviors in the female-male disparity in obesity incidence in US black and white young adults. Obesity (Silver Spring). Jul 2010;18(7):1429–36. doi:10.1038/oby.2009.362.19875993 | Age of all participants at intervention/exposure
733 | Roche ML, Creed-Kanashiro HM, Tuesta I, Kuhnlein HV. Infant and young child feeding in the Peruvian Amazon: the need to promote exclusive breastfeeding and nutrient-dense traditional complementary foods. Matern Child Nutr. Jul 2011;7(3):284–94. doi:10.1111/j.17408709.2009.00234.x.21689271 | Study design; Intervention/exposure
734 | Roche ML, Marquis GS, Gyorkos TW, Blouin B, Sarsoza J, Kuhnlein HV. A Community-Based Positive Deviance/Hearth Infant and Young Child Nutrition Intervention in Ecuador Improved Diet and Reduced Underweight. J Nutr Educ Behav. Mar 2017;49(3):196–203.e1. doi: 10.1016/j.jneb.2016.10.007.27843127 | Intervention/exposure
735 | Rockett HR. Family dinner: more than just a meal. J Am Diet Assoc. 2007;107(9):1498–1501. doi: 10.1016/j.jada.2007.07.004 17761226 | Study design; Publication status
736 | Rodenburg G, Kremers SP, Oenema A, van de Mheen D. Associations of parental feeding styles with child snacking behaviour and weight in the context of general parenting. Public Health Nutr. May 2014;17(5):960–9. doi:10.1017/s1368980013000712.23527513 | Age of all participants at intervention/exposure
737 | Roemmich JN, White TM, Paluch R, Epstein LH. Energy intake, parental control of children's eating, and physical activity in siblings discordant for adiposity. Appetite. Oct 2010;55(2):325–31. doi:10.1016/j.appet.2010.07.004.20633585 | Study design
738 | Rogers S, Ramsay M, Blissett J. The Montreal Children's Hospital Feeding Scale: Relationships with parental report of child eating behaviours and observed feeding interactions. Appetite. Jun 1 2018;125:201–209. doi:10.1016/j.appet.2018.02.007.29428545 | Study design; Outcome
739 | Rogers SL, Blissett J. Breastfeeding duration and its relation to weight gain, eating behaviours and positive maternal feeding practices in infancy. Article. Appetite. 2017;108:399–406. doi:10.1016/j.appet.2016.10.020.27756634 | Intervention/exposure; Outcome
740 | Rojo M, Lacruz T, Solano S, Family-reported barriers and predictors of short-term attendance in a multidisciplinary intervention for managing childhood obesity: a psycho-familysystem based randomised controlled trial (ENTREN-F). Journal article. European eating disorders review. 2022;30(6):746–759. doi:10.1002/erv.2913.35644038 | Intervention/exposure; Outcome
741 | Rollins BY, Loken E, Savage JS, Birch LL. Effects of restriction on children’s intake differ by child temperament, food reinforcement, and parent’s chronic use of restriction. Appetite. Feb 2014;73:31–9.doi:10.1016/j.appet.2013.10.005.24511616 | Outcome
742 | Rollins BY, Loken E, Savage JS, Birch LL. Maternal controlling feeding practices and girls' inhibitory control interact to predict changes in BMI and eating in the absence of hunger from 5 to 7 y. Am J Clin Nutr. Feb 2014;99(2):249–57. doi:10.3945/ajcn.113.063545.24284443 | Study design; Intervention/exposure
743 | Roos E, Pajunen T, Ray C, Does eating family meals and having the television on during dinner correlate with overweight? A sub-study of the PRO GREENS project, looking at children from nine European countries. Public Health Nutr. Nov 2014;17(11):2528–36. doi:10.1017/s1368980013002954.24642340 | Study design
744 | Rosal MC, Lemon SC, Borg A, The Healthy Kids & Families study: Outcomes of a 24month childhood obesity prevention intervention [published correction appears in Prev Med Rep. 2023 Jun 22;35:102295. doi: 10.1016/j.pmedr.2023.102295]. Prev Med Rep. 2022;31:102086. Published 2022 Dec 7. doi:10.1016/j.pmedr.2022.102086 36820371 | Intervention/exposure
745 | Rosenkranz RR, Dzewaltowski DA. Model of the home food environment pertaining to childhood obesity. Nutr Rev. 2008;66(3): 123–140. doi:10.1111/j.1753-4887.2008.00017.x 18289177 | Publication status
746 | Ruel MT, Menon P. Child feeding practices are associated with child nutritional status in Latin America: innovative uses of the demographic and health surveys. J Nutr. Jun 2002;132(6):1180 7. doi:10.1093/jn/132.6.1180.12042431 | Intervention/exposure
747 | Ruggiero CF, Marini ME, Llewellyn CH, McHale SM, Paul IM, Savage JS. Differences in sibling temperament are associated with differences in maternal use of food to soothe during infancy: A sibling analysis. Pediatr Obes. 2022;17(8):e12907. doi:10.1111/ijpo.12907 35243805 | Outcome
748 | Russell CG, Haszard JJ, Taylor RW, Heath AM, Taylor B, Campbell KJ. Parental feeding practices associated with children's eating and weight: What are parents of toddlers and preschool children doing? Appetite. Sep 1 2018;128:120–128. doi:10.1016/j.appet.2018.05.145.29842967 | Study design
749 | Russell SJ, Hope S, Croker H, Packer J, Viner RM. Is it possible to model the impact of calorie-reduction interventions on childhood obesity at a population level and across the range of deprivation: Evidence from the Avon Longitudinal Study of Parents and Children (ALSPAC). Article. PLoS ONE. 2022;17(1January). doi:10.1371/journal.pone.0263043. | Study design; Intervention/exposure
750 | Saavedra JM, Deming D, Dattilo A, Reidy K. Lessons from the feeding infants and toddlers study in North America: what children eat, and implications for obesity prevention. Ann Nutr Metab. 2013;62 Suppl 3:27–36. doi:10.1159/000351538.23970213 | Study design; Intervention/exposure
751 | Saelens BE, Ernst MM, Epstein LH. Maternal child feeding practices and obesity: a discordant sibling analysis. Int J Eat Disord. May 2000;27(4):459–63. doi:10.1002/(sici)1098-108x(200005)27:4<459::aid-eat11>3.0.co;2-c.10744853 | Study design
752 | Salsberry PJ, Reagan PB. Dynamics of early childhood overweight. Pediatrics. Dec 2005;116(6):1329–38. doi:10.1542/peds.2004-2583.16322155 | Intervention/exposure
753 | Saltzman JA, Pineros-Leano M, Liechty JM, Bost KK, Fiese BH. Eating, feeding, and feeling: emotional responsiveness mediates longitudinal associations between maternal binge eating, feeding practices, and child weight. Int J Behav Nutr Phys Act. Aug 2 2016;13:89. doi:10.1186/s12966-016-0415-5.27484590 | Intervention/exposure; Outcome
754 | Salvo D, Ranjit N, Nielsen A, Akhavan N, van den Berg A. Characterizing Micro-scale Disparities in Childhood Obesity: Examining the Influence of Multilevel Factors on 4-Year Changes in BMI, Healthy Eating, and Physical Activity, Among a Cohort of Children Residing in Disadvantaged Urban Enclaves. Front Public Health. 2019;7:301. doi:10.3389/fpubh.2019.00301.31750284 | Intervention/exposure
755 | Sandvik P, Kuronen S, Reijs Richards H, Associations of preschoolers' dietary patterns with eating behaviors and parental feeding practices at a 12-month follow-up of obesity treatment. Appetite. 2022;168:105724. doi:10.1016/j.appet.2021.105724 34606942 | Outcome
756 | Santiago-Torres M, Cui Y, Adams AK, Structural equation modeling of the associations between the home environment and obesity-related cardiovascular fitness and insulin resistance among Hispanic children. Appetite. Jun 1 2016;101:23–30. doi:10.1016/j.appet.2016.02.003.26850309 | Study design
757 | Santos I, Victora CG, Martines J, Nutrition counseling increases weight gain among Brazilian children. J Nutr. Nov 2001;131(11):2866–73.. doi:10.1093/jn/131.11.2866.11694610 | Intervention/exposure; Outcome
758 | Sasaki A, Yorifuji T, Iwase T, Komatsu H, Takao S, Doi H. Is There Any Association between TV Viewing and Obesity in Preschool Children in Japan? Acta Med Okayama. Apr 2010;64(2):137–42. doi:10.18926/amo/32854.20424669 | Study design; Intervention/exposure
759 | Sato AF, Jelalian E, Hart CN, Associations between parent behavior and adolescent weight control. J Pediatr Psychol. May 2011;36(4):451–60. doi:10.1093/jpepsy/jsq105.21112925 | Age of all participants at intervention/exposure
760 | Satter EM, Rollins BY, Loken E. Testing Satter's Division of Responsibility in Feeding in the context of restrictive snack-management practices...Rollins BY, Loken E, Savage JS, Birch LL. Maternal controlling feeding practices and girls’ inhibitory control interact to predict changes in BMI and eating in the absence of hunger from 5 to 7 y. Am J Clin Nutr 2014;99:249–57. American Journal of Clinical Nutrition. 2014;100(3):986–987.25142891 | Study design; Publication status
761 | Savage JS, Hochgraf AK, Loken E, INSIGHT responsive parenting educational intervention for firstborns is associated with growth of second-born siblings [published correction appears in Obesity (Silver Spring). 2022 Apr;30(4):954. doi: 10.1002/oby.23398]. Obesity (Silver Spring). 2022;30(1):183–190. doi:10.1002/oby.23301 34932886 | Intervention/exposure
762 | Savage JS, Birch LL, Marini M, Anzman-Frasca S, Paul IM. Effect of the INSIGHT Responsive Parenting Intervention on Rapid Infant Weight Gain and Overweight Status at Age 1 Year: A Randomized Clinical Trial. JAMA Pediatr. Aug 1 2016;170(8):742–9. doi:10.1001/jamapediatrics.2016.0445.27271455 | Age of all participants at intervention/exposure
763 | Savage JS, Moore AM, Kling SMR, Coordination between Primary Care and Women, Infants, and Children to Prevent Obesity for Infants from Low-Income Families: A Pragmatic Randomized Clinical Trial. Child Obes. Nov 11 2022. doi:10.1089/chi.2022.0137. | Age of all participants at intervention/exposure
764 | Saxon TF, Gollapalli A, Mitchell MW, Stanko S. Demand feeding or schedule feeding: Infant growth from birth to 6 months. Article. Journal of Reproductive and Infant Psychology. 2002;20(2):89–99. | Study design; Publication status
765 | Scheiwe A, Hardy R, Watt RG. Four-year follow-up of a randomized controlled trial of a social support intervention on infant feeding practices. Matern Child Nutr. Oct 2010;6(4):328–37. doi:10.1111/j.1740-8709.2009.00231.x.21050387 | Intervention/exposure
766 | Schrempft S, van Jaarsveld CHM, Fisher A, Fildes A, Wardle J. Maternal characteristics associated with the obesogenic quality of the home environment in early childhood. Appetite. Dec 1 2016;107:392–397. doi:10.1016/j.appet.2016.08.108.27554185 | Outcome
767 | Schroeder N, Rushovich B, Bartlett E, Sharma S, Gittelsohn J, Caballero B. Early Obesity Prevention: A Randomized Trial of a Practice-Based Intervention in 0–24-Month Infants. J Obes. 2015;2015:795859. doi:10.1155/2015/795859.26078877 | Intervention/exposure
768 | Schwartz MB, Gilstad-Hayden K, Henderson KE, The Relationship between Parental Behaviors and Children's Sugary Drink Consumption Is Moderated by a Television in the Child's Bedroom. Child Obes. Oct 2015;11(5):560–8. doi:10.1089/chi.2014.0041.26317365 | Intervention/exposure; Outcome
769 | Schwartz R, Vigo Á, e Oliveira LD, Justo Giugliani ER. The Effect of a Pro-Breastfeeding and Healthy Complementary Feeding Intervention Targeting Adolescent Mothers and Grandmothers on Growth and Prevalence of Overweight of Preschool Children. PLoS One. 2015;10(7):e0131884. doi:10.1371/journal.pone.0131884.26161657 | Intervention/exposure
770 | Seal N, Broome ME. Prepregnancy Body Mass Index and Feeding Practices in Relation to Infants' Growth. J Nurse Pract. May 1 2013;9(5). doi:10.1016/j.nurpra.2013.01.017. | Study design
771 | Sedibe MH, Pisa PT, Feeley AB, Pedro TM, Kahn K, Norris SA. Dietary Habits and Eating Practices and Their Association with Overweight and Obesity in Rural and Urban Black South African Adolescents. Nutrients. Jan 29 2018;10(2). doi:10.3390/nu10020145. | Study design
772 | Seher CL. Parent-child interaction during feeding: how it may influence kids' weight and relationship with food. Today's Dietitian. 2011;13(4):32–37. | Publication status
773 | Selzam S, McAdams TA, Coleman JRI, Evidence for gene-environment correlation in child feeding: Links between common genetic variation for BMI in children and parental feeding practices. PLoS Genet. Nov 2018;14(11):e1007757. doi:10.1371/journal.pgen.1007757.30457987 | Bidirectional; Age of all participants at intervention/exposure
774 | Sen B. Frequency of family dinner and adolescent body weight status: evidence from the national longitudinal survey of youth, 1997. Obesity (Silver Spring). Dec 2006;14(12):2266–76. doi:10.1038/oby.2006.266.17189555 | Age of all participants at intervention/exposure
775 | Senarath U, Dibley MJ. Complementary feeding practices in South Asia: analyses of recent national survey data by the South Asia Infant Feeding Research Network. Matern Child Nutr. Jan 2012;8 Suppl 1(Suppl 1):5–10. doi:10.1111/j.1740-8709.2011.00371.x.22168515 | Country
776 | Seo DC, Lee CG. Association of school nutrition policy and parental control with childhood overweight. J Sch Health. Jun 2012;82(6):285–93. doi:10.1111/j.1746-1561.2012.00699.x.22568464 | Study design
777 | Sepúlveda AR, Solano S, Blanco M, Lacruz T, Veiga O. Feasibility, acceptability, and effectiveness of a multidisciplinary intervention in childhood obesity from primary care: nutrition, physical activity, emotional regulation, and family. Journal article. European eating disorders review. 2020;28(2):184–198doi:10.1002/erv.2702.31802570 | Intervention/exposure
778 | Sepúlveda MJ, Lu C, Sill S, Young JM, Edington DW. An observational study of an employer intervention for children's healthy weight behaviors. Pediatrics. Nov 2010;126(5):e1153–60. doi:10.1542/peds.2009-3210.20921066 | Intervention/exposure; Outcome
779 | Serene TE, Shamarina S, Mohd NM. Familial and socio-environmental predictors of overweight and obesity among primary school children in Selangor and Kuala Lumpur. Malays J Nutr. 2011;17(2):151–162.22303570 | Study design
780 | Shah NB, Fenick AM, Rosenthal MS. A Healthy Weight for Toddlers? Two-Year Follow-up of a Randomized Controlled Trial of Group Well-Child Care. Clin Pediatr (Phila). Dec 2016;55(14):1354–1357. doi:10.1177/0009922815623230.26823557 | Intervention/exposure
781 | Sharma M, Kanani S. Grandmothers' influence on child care. Article. Indian Journal of Pediatrics. 2006;73(4):295–298. doi:10.1007/BF02825822.16816489 | Country
782 | Shelton D, Le Gros K, Norton L, Stanton-Cook S, Morgan J, Masterman P. Randomised controlled trial: A parent-based group education programme for overweight children. J Paediatr Child Health. Dec 2007;43(12):799–805. doi:10.1111/j.1440-1754.2007.01150.x.17854421 | Intervention/exposure; Country
783 | Sherrard A, Vang M, Tan CC. Children's media use and food approach behavior: Associations with temperament and food parenting. Appetite. Mar 1 2023;182:106444. doi:10.1016/j.appet.2022.106444.36592796 | Study design
784 | Sherwood NE, JaKa MM, Crain AL, Martinson BC, Hayes MG, Anderson JD. Pediatric Primary Care-Based Obesity Prevention for Parents of Preschool Children: A Pilot Study. Child Obes. Dec 2015;11(6):674–82. doi:10.1089/chi.2015.0009.26478951 | Intervention/exposure; Outcome
785 | Shi C, Li N, Dong J, Association between maternal nonresponsive feeding practice and child's eating behavior and weight status: children aged 1 to 6 years. Eur J Pediatr. Dec 2017;176(12):1603–1612. doi:10.1007/s00431-017-3007-8.28890989 | Study design
786 | Shi H, Chen J. SUN-P230: Insight from Analysis of Feeding Practices and Growth Outcomes Among Tibetan Children Less Than 3 Years of age: what, Why and How? Clinical Nutrition. 2017;36:S139-S139. doi:10.1016/S0261-5614(17)30398-9. | Intervention/exposure; Publication status
787 | Shloim N, Rudolf M, Feltbower RG, Mohebati L, Hetherington M. Breast is best: Positive mealtime interactions in breastfeeding mothers from Israel and the United Kingdom. Health Psychol Open. Jan 2015;2(1):2055102915579605. doi:10.1177/2055102915579605.28070352 | Study design; Outcome
788 | Shloim N. Pregnancy and beyond - the role of BMI in predicting body satisfaction, eating behaviour and infant feeding across two countries. Pregnancy Hypertens. Jul 2014;4(3):237–8. doi:10.1016/j.preghy.2014.03.026. | Publication status
789 | Shrewsbury VA, Nguyen B, O'Connor J, Short-term outcomes of community-based adolescent weight management: The Loozit^®^ Study. BMC Pediatr. Feb 8 2011;11:13. doi:10.1186/1471-2431-11-13.21303505 | Study design; Intervention/exposure
790 | Shriver LH, Eagleton S, Lawless MC, Buehler C, Wideman L, Leerkes EM. Infant appetite and weight gain in early infancy: Moderating effects of controlling feeding styles. Appetite. 2022;176:106139. doi:10.1016/j.appet.2022.106139 35718312 | Intervention/exposure
791 | Shriver LH, Hubbs-Tait L, Harrist AW, Topham G, Page M. Child gender and weight status moderate the relation of maternal feeding practices to body esteem in 1st grade children. Appetite. Jun 2015;89:62–9. doi:10.1016/j.appet.2015.01.017.25624022 | Study design; Outcome
792 | Sigman-Grant M, Hayes J, VanBrackle A, Fiese B. Family Resiliency: A Neglected Perspective in Addressing Obesity in Young Children. Childhood Obesity. 2015;11(6):664–673. doi:10.1089/chi.2014.0107.26447935 | Study design
793 | Singh S, Cordeiro A, Epel E, Association between maternal eating and young child feeding in a community sample. BMC Pregnancy Childbirth. Jun 24 2023;23(1):470. doi:10.1186/s12884-023-05786-0.37355578 | Intervention/exposure; Outcome
794 | Sinton MM, Birch LL. Weight status and psychosocial factors predict the emergence of dieting in preadolescent girls. Int J Eat Disord. Dec 2005;38(4):346–54. doi:10.1002/eat.20176.16231357 | Intervention/exposure; Outcome
795 | Sirikulchayanonta C, Boonmee K, Temcharoen P, Srisorrachata S. Birth weight doubling time of Thai infants. Singapore Med J. 2002;43(7):350–353.12437042 | Intervention/exposure
796 | Slater J, Mudryj AN. Nurturing Future Generations: Household Food Practices of Canadian Children and Family Meal Participation. Can J Diet Pract Res. Sep 2016;77(3):113–8. doi:10.3148/cjdpr-2015-050.26916735 | Study design
797 | Slater J, Sevenhuysen G, Edginton B, O'Neil J. 'Trying to make it all come together': structuration and employed mothers' experience of family food provisioning in Canada. Health Promot Int. Sep 2012;27(3):405–15. doi:10.1093/heapro/dar037.21693474 | Study design
798 | Sleddens E, Mâsse L, Kremers S, Validation of the Comprehensive General Parenting Questionnaire and associations with children's eating behavior and BMI. Appetite. 2016;101:224–224. | Publication status
799 | Small L, Bonds-McClain D, Vaughan L, Melnyk B, Gannon A, Thompson S. A parent-directed portion education intervention for young children: Be Beary Healthy. Journal for Specialists in Pediatric Nursing. 2012;17(4):312–320.23009043 | Study design; Intervention/exposure; Outcome
800 | Smith AD, Sanchez N, Harrison K, Observations of parent-adolescent interactions relate to food parenting practices and adolescent disordered eating in adolescents at risk for adult obesity. Fam Process. Nov 8 2022. doi:10.1111/famp.12829. | Study design; Outcome
801 | Smith AR, Eiden RD, Shisler S, Paluch RA, Piazza J, Kong KL. The effects of a music enrichment program on parent-infant interactions during mealtime: A randomized controlled trial. Appetite. Aug 1 2023;187:106590. doi:10.1016/j.appet.2023.106590.37148975 | Intervention/exposure
802 | Smith JD, Carroll AJ, Fu E, Berkel C. Baseline Targeted Moderation in a Trial of the Family Check-Up 4 Health: Potential Explanations for Finding Few Practical Effects. Prev Sci. Feb 2023;24(2):226–236. doi:10.1007/s11121-021-01266-z.34159507 | Study design; Intervention/exposure
803 | Somaraki M, Eli K, Ek A, Sandvik P, Sorjonen K, Nowicka P. Changes in parental feeding practices and children's food intake: a randomized control trial of obesity treatment in preschoolers. Journal article; Conference proceeding. Obesity research & clinical practice. 2019;13(3):323. | Publication status
804 | Somaraki M, Ek A, Eli K, Parenting and childhood obesity: Validation of a new questionnaire and evaluation of treatment effects during the preschool years. PLoS One. 2021;16(9):e0257187. doi:10.1371/journal.pone.0257187.34555050 | Intervention/exposure; Outcome
805 | Somaraki M, Eli K, Sorjonen K, Ek A, Sandvik P, Nowicka P. Changes in parental feeding practices and preschoolers' food intake following a randomized controlled childhood obesity trial. Appetite. Nov 1 2020;154:104746. doi:10.1016/j.appet.2020.104746.32446880 | Bidirectional
806 | Soto SC, Arredondo EM, Horton LA, Ayala GX. Validation of the modified Parenting Strategies for Eating and Physical Activity Scale-Diet (PEAS-Diet) in Latino children. Appetite. Mar 1 2016;98:55–62. doi:10.1016/j.appet.2015.12.003.26699670 | Study design; Outcome
807 | Spears-Lanoix EC, McKyer EL, Evans A, Using Family-Focused Garden, Nutrition, and Physical Activity Programs To Reduce Childhood Obesity: The Texas! Go! Eat! Grow! Pilot Study. Child Obes. Dec 2015;11(6):707–14. doi:10.1089/chi.2015.0032.26655452 | Study design; Intervention/exposure
808 | Speirs KE, Hayes JT, Musaad S, VanBrackle A, Sigman-Grant M. Is family sense of coherence a protective factor against the obesogenic environment? Appetite. Apr 1 2016;99:268–276. doi:10.1016/j.appet.2016.01.025.26796029 | Study design
809 | Spence AC, Campbell KJ, Crawford DA, McNaughton SA, Hesketh KD. Mediators of improved child diet quality following a health promotion intervention: the Melbourne InFANT Program. Int J Behav Nutr Phys Act. Nov 4 2014;11:137. doi:10.1186/s12966-014-0137-5.25366542 | Outcome
810 | Spruijt-Metz D, Li C, Cohen E, Birch L, Goran M. Longitudinal influence of mother's child-feeding practices on adiposity in children. J Pediatr. Mar 2006;148(3):314–20. doi:10.1016/j.jpeds.2005.10.035.16615957 | Age of all participants at intervention/exposure
811 | Spruijt-Metz D, Lindquist CH, Birch LL, Fisher JO, Goran MI. Relation between mothers' child-feeding practices and children's adiposity. Am J Clin Nutr. Mar 2002;75(3):581–6. doi:10.1093/ajcn/75.3.581.11864866 | Study design
812 | Srivastava D, Zheng LR, Dev DA. Examining correlates of feeding practices among parents of preschoolers. Nutr Health. Aug 23 2021:2601060211032886. doi:10.1177/02601060211032886. | Study design
813 | Srivastava G, Palmer KD, Ireland KA, Shape-Up and Eat Right Families Pilot Program: Feasibility of a Weight Management Shared Medical Appointment Model in African-Americans With Obesity at an Urban Academic Medical Center. Front Pediatr. 2018;6:101. doi:10.3389/fped.2018.00101.29707530 | Intervention/exposure
814 | Stang J, Rehorst J, Golicic M. Parental feeding practices and risk of childhood overweight in girls: implications for dietetics practice. J Am Diet Assoc. 2004;104(7):1076–1079. doi:10.1016/j.jada.2004.03.030 15215764 | Study design; Publication date
815 | Stang J, Loth KA. Parenting style and child feeding practices: potential mitigating factors in the etiology of childhood obesity. J Am Diet Assoc. 2011;111(9):1301–1305. doi:10.1016/j.jada.2011.06.010 21872692 | Study design; Publication status
816 | Stea TH, Vik FN, Bere E, Svendsen MV, Oellingrath IM. Meal pattern among Norwegian primary-school children and longitudinal associations between meal skipping and weight status. Public Health Nutr. Feb 2015;18(2):286–91. doi:10.1017/s136898001400010x.24521714 | Intervention/exposure
817 | Steele RG, Jensen CD, Gayes LA, Leibold HC. Medium is the message: moderate parental control of feeding correlates with improved weight outcome in a pediatric obesity intervention. J Pediatr Psychol. Aug 2014;39(7):708–17. doi:10.1093/jpepsy/jsu035.24914085 | Age of all participants at intervention/exposure
818 | Steinsbekk S, Belsky J, Wichstrøm L. Parental Feeding and Child Eating: An Investigation of Reciprocal Effects. Child Dev. Sep 2016;87(5):1538–49. doi:10.1111/cdev.12546.27154834 | Outcome
819 | Steinsbekk S, Odegård R, Wichstrøm L. Treatment of obesity in children: Parent's perceived emotional barriers as predictor of change in body fat. Obes Res Clin Pract. Jul-Sep 2011;5(3):e169–266. doi:10.1016/j.orcp.2011.03.001. | Intervention/exposure
820 | Sterling W, Crosbie C, Shaw N, Martin S. The Use of the Plate-by-Plate Approach for Adolescents Undergoing Family-Based Treatment. Journal of the Academy of Nutrition & Dietetics. 2019;119(7):1075–1084. doi:10.1016/j.jand.2018.06.011.30213619 | Publication status
821 | Stifter CA, Anzman-Frasca S, Birch LL, Voegtline K. Parent use of food to soothe infant/toddler distress and child weight status. An exploratory study. Appetite. Dec 2011;57(3):693–9. doi:10.1016/j.appet.2011.08.013.21896298 | Study design
822 | Stifter CA, Moding KJ. Infant temperament and parent use of food to soothe predict change in weight-for-length across infancy: early risk factors for childhood obesity. Int J Obes (Lond). Sep 2018;42(9):1631–1638. doi:10.1038/s41366-018-0006-4.29463917 | Age of all participants at intervention/exposure
823 | Stifter CA, Moding KJ. Understanding and measuring parent use of food to soothe infant and toddler distress: A longitudinal study from 6 to 18 months of age. Appetite. 2015;95:188–196. doi:10.1016/j.appet.2015.07.009 26164121 | Age of all participants at intervention/exposure
824 | Strazdins L, Dinh H, Banwell C, D'Este C, Zulfiqar T. Drivers of Overweight/Obesity in 4–11 Year Old Children of Australians and Immigrants; Evidence from Growing Up in Australia. Journal of Immigrant & Minority Health. 2019;21(4):737–750. doi:10.1007/s10903-018-0841-3.30484000 | Intervention/exposure
825 | Suaib F. Family empowerment through psychosocial stimulation assistance and child feeding in increasing nutrition intake and body weight of children 2–3 years old to prevent stunting. Article. Indian Journal of Forensic Medicine and Toxicology. 2021;15(3):4339–4344. | Country
826 | Sud S, Tamayo NC, Faith MS, Keller KL. Increased restrictive feeding practices are associated with reduced energy density in 4–6-year-old, multi-ethnic children at ad libitum laboratory test-meals. Appetite. Oct 2010;55(2):201–7. doi:10.1016/j.appet.2010.05.089.20594990 | Study design
827 | Suder A, Janusz M, Jagielski P, Prevalence and risk factors of abdominal obesity in Polish rural children. Homo. Aug 2015;66(4):357–68. doi:10.1016/j.jchb.2014.09.008.25796137 | Study design; Intervention/exposure
828 | Suglia SF, Duarte CS, Chambers EC, Boynton-Jarrett R. Social and behavioral risk factors for obesity in early childhood. J Dev Behav Pediatr. Oct 2013;34(8):549–56. doi:10.1097/DBP.0b013e3182a509c0.24131877 | Intervention/exposure
829 | Sutin AR, Terracciano A. Mother and child personality traits associated with common feeding strategies and child body mass index. Appetite. Jun 1 2018;125:295–301. doi:10.1016/j.appet.2018.02.009.29454016 | Study design; Comparator
830 | Sweeney AM, Wilson DK, Loncar H, Brown A. Secondary benefits of the families improving together (FIT) for weight loss trial on cognitive and social factors in African American adolescents. Int J Behav Nutr Phys Act. May 24 2019;16(1):47. doi:10.1186/s12966-019-0806-5.31126345 | Study design
831 | Tabak RG, Morshed AB, Schwarz CD, Haire-Joshu D. Impact of a Healthy Weight Intervention Embedded Within a National Home Visiting Program on the Home Food Environment. Front Public Health. 2018;6:178. doi:10.3389/fpubh.2018.00178.29998092 | Outcome
832 | Tabak RG, Schwarz CD, Haire-Joshu DL. Associations between feeding practices and maternal and child weight among mothers who do and do not correctly identify their child's weight status. Obes Sci Pract. Mar 2017;3(1):51–58. doi:10.1002/osp4.88.31516723 | Study design
833 | Tabbakh T, Freeland-Graves J. Development and validation of the Multidimensional Home Environment Scale (MHES) for adolescents and their mothers. Eat Behav. Aug 2016;22:76–82. doi:10.1016/j.eatbeh.2016.03.031.27089386 | Study design; Outcome
834 | Tabbakh T, Freeland-Graves JH. The home environment: A mediator of nutrition knowledge and diet quality in adolescents. Appetite. Oct 1 2016;105:46–52. doi:10.1016/j.appet.2016.05.002.27170447 | Study design; Intervention/exposure
835 | Tak NI, Te Velde SJ, Oenema A, The association between home environmental variables and soft drink consumption among adolescents. Exploration of mediation by individual cognitions and habit strength. Appetite. Apr 2011;56(2):503–10. doi:10.1016/j.appet.2011.01.013.21241761 | Study design; Outcome
836 | Tan CC, Holub SC. Children's self-regulation in eating: associations with inhibitory control and parents' feeding behavior. J Pediatr Psychol. Apr 2011;36(3):340–5. doi:10.1093/jpepsy/jsq089.20926406 | Study design; Intervention/exposure; Outcome
837 | Tanasescu M, Ferris AM, Himmelgreen DA, Rodriguez N, Pérez-Escamilla R. Biobehavioral factors are associated with obesity in Puerto Rican children. J Nutr. Jul 2000;130(7):1734–42. doi:10.1093/jn/130.7.1734.10867044 | Study design; Intervention/exposure
838 | Tanja TT, Outi N, Sakari S, Jarmo L, Kaisa P, Leila K. Preliminary Finnish measures of eating competence suggest association with health-promoting eating patterns and related psychobehavioral factors in 10–17 year old adolescents. Nutrients. May 21 2015;7(5):3828–46. doi:10.3390/nu7053828.26007335 | Study design
839 | Tarro S, Lahdenperä M, Vahtera J, Pentti J, Lagström H. Parental feeding practices and child eating behavior in different socioeconomic neighborhoods and their association with childhood weight. The STEPS study. Health Place. 2022;74:102745. doi:10.1016/j.healthplace.2022.102745 35247796 | Study design
840 | Tatone-Tokuda F, Dubois L, Girard M. Psychosocial determinants of the early introduction of complementary foods. Health Educ Behav. Apr 2009;36(2):302–20. doi:10.1177/1090198107303307.17620664 | Intervention/exposure; Outcome
841 | Taveras EM, Gillman MW, Kleinman K, Rich-Edwards JW, Rifas-Shiman SL. Racial/ethnic differences in early-life risk factors for childhood obesity. Pediatrics. Apr 2010;125(4):686–95. doi:10.1542/peds.2009-2100.20194284 | Outcome
842 | Taveras EM, Rifas-Shiman SL, Berkey CS, Family dinner and adolescent overweight. Obes Res. May 2005;13(5):900–6. doi:10.1038/oby.2005.104.15919844 | Age of all participants at intervention/exposure
843 | Taveras EM, Rifas-Shiman SL, Scanlon KS, Grummer-Strawn LM, Sherry B, Gillman MW. To what extent is the protective effect of breastfeeding on future overweight explained by decreased maternal feeding restriction? Pediatrics. Dec 2006;118(6):2341–8. doi:10.1542/peds.2006-1814.17142517 | Age of all participants at intervention/exposure
844 | Taveras EM, Scanlon KS, Birch L, Rifas-Shiman SL, Rich-Edwards JW, Gillman MW. Association of breastfeeding with maternal control of infant feeding at age 1 year. Pediatrics. Nov 2004;114(5):e577–83. doi:10.1542/peds.2004-0801.15492358 | Outcome
845 | Tay CW, Chin YS, Lee ST, Khouw I, Poh BK. Association of Eating Behavior With Nutritional Status and Body Composition in Primary School-Aged Children. Asia Pac J Public Health. Jul 2016;28(5 Suppl):47s–58s. doi:10.1177/1010539516651475.27252248 | Study design
846 | Taylor A, Wilson C, Slater A, Mohr P. Parent- and child-reported parenting. Associations with child weight-related outcomes. Appetite. Dec 2011;57(3):700–6. doi:10.1016/j.appet.2011.08.014.21896297 | Study design
847 | Taylor NJ, Sahota P, Sargent J, Using intervention mapping to develop a culturally appropriate intervention to prevent childhood obesity: the HAPPY (Healthy and Active Parenting Programme for Early Years) study. Int J Behav Nutr Phys Act. Dec 28 2013;10:142. doi:10.1186/1479-5868-10-142.24373301 | Study design; Outcome
848 | Taylor RW, Heath A-LM, Haszard JJ. A Baby-Led Approach to Complementary Feeding...Taylor RW, Williams SM, Fangupo LJ, Effect of a baby-led approach to complementary feeding on infant growth and overweight: a randomized clinical trial. JAMA Pediatr. 2017;171(9):838–846. JAMA Pediatrics. 2018;172(2):197–198. doi:10.1001/jamapediatrics.2017.4683. | Intervention/exposure
849 | Taylor RW, Williams SM, Fangupo LJ, Effect of a baby-led approach to complementary feeding on infant growth and overweight: A randomized clinical trial. Article. JAMA Pediatrics. 2017;171(9):838–846doi:10.1001/jamapediatrics.2017.1284.28692728 | Intervention/exposure; Comparator
850 | Tengkawan J, Septisari AA, Ihyauddin Z, Improving knowledge, attitude, and practices of complementary feeding using practical intervention training for parents living in central Lombok, Indonesia: A community-based study. Article. WHO South-East Asia journal of public health. 2022;11(1):54–60. doi:10.4103/WHO-SEAJPH.WHO-SEAJPH_336_20.36308273 | Intervention/exposure
851 | Terán LM, Belkic KL, Johnson CA. An exploration of psychosocial determinants of obesity among Hispanic women. Hispanic Journal of Behavioral Sciences. 2002;24(1):92–103. | Study design; Age of some participants at I/E
852 | Theim KR, Sinton MM, Stein RI, Preadolescents' and parents' dietary coping efficacy during behavioral family-based weight control treatment. J Youth Adolesc. 2012;41(1):86–97. doi:10.1007/s10964-011-9728-5 22081241 | Intervention/exposure
853 | Thøgersen-Ntoumani C, Ng JY, Ntoumanis N, 'Mum's the word': Predictors and outcomes of weight concerns in pre-adolescent and early adolescent girls. Body Image. Mar 2016;16:107–12. doi:10.1016/j.bodyim.2015.12.004.26803392 | Study design; Intervention/exposure
854 | Thompson AL, Adair LS, Bentley ME. Pressuring and restrictive feeding styles influence infant feeding and size among a low-income African-American sample. Obesity (Silver Spring). Mar 2013;21(3):562–71. doi:10.1002/oby.20091.23592664 | Age of all participants at intervention/exposure
855 | Thompson AL, Jahnke JR, Teran E, Bentley ME. Pathways linking maternal mental health and child health in a dual burden context: Evidence from Galapagos, Ecuador. Article. Social Science and Medicine. 2022;305doi:10.1016/j.socscimed.2022.115043. | Intervention/exposure
856 | Thompson AL, Wasser H, Nulty A, Bentley ME. Feeding style profiles are associated with maternal and infant characteristics and infant feeding practices and weight outcomes in African American mothers and infants. Appetite. 2021;160:105084. doi:10.1016/j.appet.2020.105084 33359466 | Study design
857 | Thompson AL. Intergenerational impact of maternal obesity and postnatal feeding practices on pediatric obesity. Nutr Rev. 2013;71 Suppl 1(0 1):S55–S61. doi:10.1111/nure.12054 24147925 | Study design
858 | Timby N, Hernell O, Lönnerdal B, Domellöf M. Parental feeding control in relation to feeding mode and growth pattern during early infancy. Acta Paediatr. Oct 2014;103(10):1072–7. doi:10.1111/apa.12721.24948384 | Study design; Outcome
859 | Todd MK, Reis-Bergan MJ, Sidman CL, Effect of a family-based intervention on electronic media use and body composition among boys aged 8--11 years: a pilot study. J Child Health Care. Dec 2008;12(4):344–58. doi:10.1177/1367493508097404.19052191 | Intervention/exposure
860 | Toh JY, Quah PL, Wong CH, Evaluation of a child food reward task and its association with maternal feeding practices. PLoS One. 2021;16(7):e0254773. Published 2021 Jul 21. doi:10.1371/journal.pone.0254773 34288967 | Outcome; Country
861 | Tomayko EJ, Prince RJ, Cronin KA, Adams AK. The Healthy Children, Strong Families intervention promotes improvements in nutrition, activity and body weight in American Indian families with young children. Public Health Nutr. Oct 2016;19(15):2850–9. doi:10.1017/s1368980016001014.27211525 | Intervention/exposure
862 | Tommasi M, Toro F, Salvia A, Saggino A. Connections between Children's Eating Habits, Mental Health, and Parental Stress. J Obes. 2022;2022:6728502. doi:10.1155/2022/6728502.35463868 | Intervention/exposure
863 | Toschke AM, Thorsteinsdottir KH, von Kries R. Meal frequency, breakfast consumption and childhood obesity. Int J Pediatr Obes. 2009;4(4):242–8. doi:10.3109/17477160902763341.19922038 | Study design
864 | Toussaint N, Streppel MT, Mul S, The effects of a preschool-based intervention for Early Childhood Education and Care teachers in promoting healthy eating and physical activity in young children: A cluster randomised controlled trial. PLoS One. 2021;16(7):e0255023. Published 2021 Jul 23. doi:10.1371/journal.pone.0255023 34298547 | Intervention/exposure
865 | Tovar A, Choumenkovitch SF, Hennessy E, Low demanding parental feeding style is associated with low consumption of whole grains among children of recent immigrants. Appetite. Dec 2015;95:211–8. doi:10.1016/j.appet.2015.06.006.26122753 | Study design; Outcome
866 | Tovar A, Hennessy E, Must A, Feeding styles and evening family meals among recent immigrants. Int J Behav Nutr Phys Act. Jun 26 2013;10:84. doi:10.1186/1479-5868-10-84.23803223 | Study design
867 | Tovar A, Hennessy E, Pirie A, Feeding styles and child weight status among recent immigrant mother-child dyads. Int J Behav Nutr Phys Act. May 29 2012;9:62. doi:10.1186/1479-5868-9-62.22642962 | Study design
868 | Towner EK, Reiter-Purtill J, Boles RE, Zeller MH. Predictors of caregiver feeding practices differentiating persistently obese from persistently non-overweight adolescents. Appetite. 2015;84:120–127. doi:10.1016/j.appet.2014.08.015 25246031 | Study design
869 | Townsend E, Pitchford NJ. Baby knows best? The impact of weaning style on food preferences and body mass index in early childhood in a case-controlled sample. BMJ Open. 2012;2(1):e000298. doi:10.1136/bmjopen-2011-000298. | Study design
870 | Trang NH, Hong TK, Dibley MJ. Cohort profile: Ho Chi Minh City Youth Cohort--changes in diet, physical activity, sedentary behaviour and relationship with overweight/obesity in adolescents. BMJ Open. 2012;2(1):e000362. doi:10.1136/bmjopen-2011-000362. | Intervention/exposure; Country
871 | Tremblay L, Rinaldi CM. The prediction of preschool children's weight from family environment factors: gender-linked differences. Eat Behav. Dec 2010;11(4):266–75. doi:10.1016/j.eatbeh.2010.07.005.20850062 | Study design
872 | Tripicchio GL, Keller KL, Johnson C, Pietrobelli A, Heo M, Faith MS. Differential maternal feeding practices, eating self-regulation, and adiposity in young twins. Pediatrics. Nov 2014;134(5):e1399–404. doi:10.1542/peds.2013-3828.25311601 | Study design
873 | Troncoso Sawyer M, Duran N, Wallace SP. Exploring Food Decision Processes of Latino Families in California's Central Valley. Californian Journal of Health Promotion. 2019;17(1):31–44. doi:10.32398/cjhp.v17i1.2222. | Study design
874 | Tschann JM, Martinez SM, Penilla C, Parental feeding practices and child weight status in Mexican American families: a longitudinal analysis. Int J Behav Nutr Phys Act. May 20 2015;12:66. doi:10.1186/s12966-015-0224-2.25986057 | Age of all participants at intervention/exposure
875 | Tucker JM, DeFrang R, Orth J, Wakefield S, Howard K. Evaluation of a Primary Care Weight Management Program in Children Aged 2(−)5 years: Changes in Feeding Practices, Health Behaviors, and Body Mass Index. Nutrients. Feb 27 2019;11(3)doi:10.3390/nu11030498. | Intervention/exposure; Outcome
876 | Tung HJ, Yeh MC. Parenting style and child-feeding behaviour in predicting children's weight status change in Taiwan. Public Health Nutr. 2014;17(5):970–978. doi:10.1017/S1368980012005502 23332023 | Country
877 | Turer CB, Stroo M, Brouwer RJ, Do high-risk preschoolers or overweight mothers meet AAP-recommended behavioral goals for reducing obesity? Acad Pediatr. May-Jun 2013;13(3):243–50. doi:10.1016/j.acap.2013.01.003.23491583 | Study design
878 | Turkkahraman D, Bircan I, Tosun O, Saka O. Prevalence and risk factors of obesity in school children in Antalya, Turkey. Saudi Med J. 2006;27(7):1028–1033.16830025 | Study design
879 | Türkoğlu S, Bilgiç A, Akça Ö F. ADHD symptoms, breast-feeding and obesity in children and adolescents. Pediatr Int. Aug 2015;57(4):546–51. doi:10.1111/ped.12593.25625700 | Intervention/exposure
880 | Tur-Sinai A, Kolobov T, Tesler R, Baron-Epel O, Dvir K, Harel-Fisch Y. Associations between socioeconomic and family determinants and weight-control behaviours among adolescents. Int J Public Health. Dec 2020;65(9):1689–1698. doi:10.1007/s00038-020-01498-w.33026464 | Study design; Outcome
881 | Tylka TL, Eneli IU, Kroon Van Diest AM, Lumeng JC. Which adaptive maternal eating behaviors predict child feeding practices? An examination with mothers of 2- to 5-year-old children. Eat Behav. Jan 2013;14(1):57–63. doi:10.1016/j.eatbeh.2012.10.014.23265403 | Study design; Outcome
882 | Tylka TL, Lumeng JC, Eneli IU. Maternal intuitive eating as a moderator of the association between concern about child weight and restrictive child feeding. Appetite. Dec 2015;95:158–65. doi:10.1016/j.appet.2015.06.023.26145275 | Study design; Outcome
883 | u Plessis LM, Herselman MG, McLachlan MH, Nel JH. Selected facets of nutrition during the first 1000 days of life in vulnerable South African communities. Article. SAJCH South African Journal of Child Health. 2016;10(1):37–42. | Study design
884 | Utter J, Denny S, Dixon R, Ameratunga S, Teevale T. Family support and weight-loss strategies among adolescents reporting sustained weight loss. Public Health Nutr. Mar 2013;16(3):499–504. doi:10.1017/s1368980012002820.22687650 | Study design
885 | Utter J, Denny S, Robinson E, Fleming T, Ameratunga S, Grant S. Family meals among New Zealand young people: relationships with eating behaviors and body mass index. J Nutr Educ Behav. Jan-Feb 2013;45(1):3–11. doi:10.1016/j.jneb.2012.04.010.23110750 | Study design
886 | Utter J, Scragg R, Schaaf D, Mhurchu CN. Relationships between frequency of family meals, BMI and nutritional aspects of the home food environment among New Zealand adolescents. Int J Behav Nutr Phys Act. Oct 23 2008;5:50. doi:10.1186/1479-5868-5-50.18947431 | Study design
887 | Valero-García AV, Olmos-Soria M, Madrid-Garrido J, Martínez-Hernández I, Haycraft E. The role of regulation and emotional eating behaviour in the early development of obesity. Article. International Journal of Environmental Research and Public Health. 2021;18(22). doi:10.3390/ijerph182211884 | Study design
888 | van Ansem WJ, Schrijvers CT, Rodenburg G, van de Mheen D. Children's snack consumption: role of parents, peers and child snack-purchasing behaviour. Results from the INPACT study. Eur J Public Health. Dec 2015;25(6):1006–11. doi:10.1093/eurpub/ckv098.26045526 | Study design
889 | van de Gaar VM, Jansen W, van Grieken A, Borsboom G, Kremers S, Raat H. Effects of an intervention aimed at reducing the intake of sugar-sweetened beverages in primary school children: a controlled trial. Int J Behav Nutr Phys Act. 2014;11:98. Published 2014 Jul 25. doi:10.1186/s12966-014-0098-8 25060113 | Intervention/exposure; Outcome
890 | van de Pas KGH, Lubrecht JW, Hesselink ML, Winkens B, van Dielen FMH, Vreugdenhil ACE. The Effect of a Multidisciplinary Lifestyle Intervention on Health Parameters in Children versus Adolescents with Severe Obesity. Article. Nutrients. 2022;14(9). doi:10.3390/nu14091795. | Intervention/exposure
891 | van den Berg PA, Keery H, Eisenberg M, Neumark-Sztainer D. Maternal and adolescent report of mothers' weight-related concerns and behaviors: longitudinal associations with adolescent body dissatisfaction and weight control practices. J Pediatr Psychol. Nov 2010;35(10):1093–102. doi:10.1093/jpepsy/jsq042.20498008 | Intervention/exposure; Outcome
892 | van Deutekom AW, Chinapaw MJ, Vrijkotte TG, Gemke RJ. The association of birth weight and postnatal growth with energy intake and eating behavior at 5 years of age - a birth cohort study. Int J Behav Nutr Phys Act. Feb 4 2016;13:15. doi:10.1186/s12966-016-0335-4.26847088 | Intervention/exposure
893 | van Grieken A, Renders CM, van de Gaar VM, Hirasing RA, Raat H. Associations between the home environment and children's sweet beverage consumption at 2-year follow-up: the 'Be active, eat right' study. Pediatr Obes. Apr 2015;10(2):126–33. doi:10.1111/ijpo.235.24903408 | Outcome
894 | van Grieken A, Veldhuis L, Renders CM, Population-Based Childhood Overweight Prevention: outcomes of the 'Be Active, Eat Right' Study. Journal article. PloS one. 2013;8(5):e65376. doi:10.1371/journal.pone.0065376.23741491 | Intervention/exposure
895 | Van Lippevelde W, van Stralen M, Verloigne M, Mediating effects of home-related factors on fat intake from snacks in a school-based nutrition intervention among adolescents. Health Educ Res. Feb 2012;27(1):36–45. doi:10.1093/her/cyr110.22156234 | Study design; Outcome
896 | Van Ryzin MJ, Nowicka P. Direct and indirect effects of a family-based intervention in early adolescence on parent-youth relationship quality, late adolescent health, and early adult obesity. J Fam Psychol. Feb 2013;27(1):106–16. doi:10.1037/a0031428.23421838 | Intervention/exposure
897 | van Strien T, Snoek HM, van der Zwaluw CS, Engels RC. Parental control and the dopamine D2 receptor gene (DRD2) interaction on emotional eating in adolescence. Appetite. Apr 2010;54(2):255–61.doi:10.1016/j.appet.2007.03.227.19925838 | Study design; Outcome
898 | van Strien, T, Snoek, HM, van der Zwaluw, CS, Engels, RC. Parental control and the dopamine D2 receptor gene (DRD2) interaction on emotional eating in adolescence. Appetite. 2010. 54:255–61 . doi:10.1016/j.appet.2009.11.006.19925838 | Intervention/exposure; Outcome
899 | van Strien T, van Niekerk R, Ouwens MA. Perceived parental food controlling practices are related to obesogenic or leptogenic child life style behaviors. Appetite. Aug 2009;53(1):151–4. doi:10.1016/j.appet.2009.05.011.19467280 | Study design; Outcome
900 | van Vliet MS, Schultink JM, Jager G, The Baby's First Bites RCT: Evaluating a Vegetable-Exposure and a Sensitive-Feeding Intervention in Terms of Child Health Outcomes and Maternal Feeding Behavior During Toddlerhood. J Nutr. 2022;152(2):386–398. doi:10.1093/jn/nxab387 34791320 | Intervention/exposure
901 | Vandyousefi S, Messito MJ, Katzow MW, Scott MA, Gross RS. Infant appetite traits, feeding practices and child obesity in low-income Hispanic families. Article in Press. Pediatric Obesity. 2022;doi:10.1111/ijpo.12913 | Intervention/exposure
902 | Vandyousefi S, Messito MJ, Scott MA, Gross RS. Do Appetite Traits Mediate the Link between Birth Weight and Later Child Weight in Low-Income Hispanic Families? Article in Press. Childhood obesity (Print). 2022;doi:10.1089/chi.2022.0124 | Intervention/exposure
903 | Vandyousefi S, Gross RS, Katzow MW, Scott MA, Messito MJ. Infant and Early Child Appetite Traits and Child Weight and Obesity Risk in Low-Income Hispanic Families. J Acad Nutr Diet. Nov 2021;121(11):2210–2220. doi:10.1016/j.jand.2021.04.001.33994142 | Intervention/exposure
904 | Vanhala ML, Laitinen J, Kaikkonen K, Keinänen-Kiukaanniemi S, Korpelainen R. Parental predictors of fruit and vegetable consumption in treatment-seeking overweight children. J Hum Nutr Diet. Feb 2011;24(1):47–53. doi:10.1111/j.1365-277X.2010.01133.x.21114555 | Study design
905 | Vaughan KL, Cade JE, Hetherington MM, Evaluation of the PhunkyFoods intervention on food literacy and cooking skills of children aged 7–9 years: a cluster randomised controlled trial in Yorkshire Primary Schools UK. Article. Trials. 2022;23(1). doi:10.1186/s13063-022-06558-5. | Publication status
906 | Veltsista A, Laitinen J, Sovio U, Roma E, Järvelin MR, Bakoula C. Relationship between eating behavior, breakfast consumption, and obesity among Finnish and Greek adolescents. J Nutr Educ Behav. 2010;42(6):417–421. doi:10.1016/j.jneb.2009.12.004 20729150 | Study design; Outcome
907 | Ventura AK, Whaley SE. Strategies to promote responsive bottle-feeding in WIC predict less frequent use of food to soothe and healthier weight status for infants with negative temperaments. Pediatr Obes. 2022;17(8):e12908. doi:10.1111/ijpo.12908 35224881 | Intervention/exposure
908 | Ventura AK, Garcia P, Schaffner AA. Associations between bottle-feeding intensity and maternal encouragement of bottle-emptying. Public Health Nutr. Dec 2017;20(17):3090–3098. doi:10.1017/s1368980017002166.28893342 | Outcome
909 | Ventura AK, Hart CN, Phelan S, Jelalian E, Wing RR. Associations Between Technology Use, Responsive Feeding, and Child Temperament Among Prior Prenatal Intervention Participants. J Dev Behav Pediatr. May 1 2023;44(4):e315–e321. doi:10.1097/dbp.0000000000001174.37020323 | Study design; Outcome
910 | Ventura AK, Pollack Golen R. A pilot study comparing opaque, weighted bottles with conventional, clear bottles for infant feeding. Appetite. Feb 2015;85:178–84. doi:10.1016/j.appet.2014.11.028.25445988 | Study design; Intervention/exposure; Outcome
911 | Ventura AK, Silva Garcia K, Meza M, Rodriguez E, Martinez CE, Whaley SE. Promoting Responsive Bottle-Feeding Within WIC: Evaluation of a Policy, Systems, and Environmental Change Approach. J Acad Nutr Diet. Jun 2 2021. doi:10.1016/j.jand.2021.05.003. | Intervention/exposure; Outcome
912 | Villalobos, B, Miranda, H, Schnettler, B. Satisfaction with Food: Profiles of Two-Villalobos B, Miranda H, Schnettler B. Satisfaction with Food: Profiles of Two-Parent Families with Adolescent Children. Int J Environ Res Public Health. Dec 12 2022; 19(24). doi:10.3390/ijerph192416693. | Study design
913 | Vitolo MR, Bortolini GA, Campagnolo PD, Hoffman DJ. Maternal dietary counseling reduces consumption of energy-dense foods among infants: a randomized controlled trial. J Nutr Educ Behav. 2012;44(2):140–147. doi:10.1016/i.jneb.2011.06.012 22189004 | Intervention/exposure; Outcome
914 | Vlasblom E, van Grieken A, Beltman M, Hoir MP, Raat H, Boere-Boonekamp MM. Parenting support to prevent overweight during regular well-child visits in 0–3 year old children (BBOFT+ program), a cluster randomized trial on the effectiveness on child BMI and health behaviors and parenting. Article. PLoS ONE. 2020;15(8 August)doi:10.1371/journal.pone.0237564. | Intervention/exposure; Outcome
915 | Vogels N, Posthumus DL, Mariman EC, Determinants of overweight in a cohort of Dutch children. Am J Clin Nutr. Oct 2006;84(4):717–24. doi:10.1093/ajcn/84.4.717.17023696 | Intervention/exposure
916 | Wadhera D, Capaldi Phillips ED, Wilkie LM, Boggess MM. Perceived recollection of frequent exposure to foods in childhood is associated with adulthood liking. Appetite. Jun 2015;89:22–32. doi:10.1016/j.appet.2015.01.011.25616213 | Study design; Outcome
917 | Wald ER, Ewing LJ, Moyer SCL, Eickhoff JC. An Interactive Web-Based Intervention to Achieve Healthy Weight in Young Children. Clin Pediatr (Phila). May 2018;57(5):547–557. doi:10.1177/0009922817733703.29067819 | Study design; Intervention/exposure
918 | Walshaw CA, Owens JM, Scally AJ, Walshaw MJ. Does breastfeeding method influence infant weight gain? Arch Pis Child. Apr 2008;93(4):292–6. doi:10.1136/adc.2006.107102. | Age of all participants at intervention/exposure
919 | Walton K, Filion AJ, Darlington G, Morrongiello B, Haines J. Parents and tots together: adaptation of a family-based obesity prevention intervention to the Canadian context. Journal article; Conference proceeding. Canadian journal of diabetes. 2015;39:S72–S73. | Publication status
920 | Walton K, Kuczynski L, Haycraft E, Breen A, Haines J. Time to re-think picky eating?: a relational approach to understanding picky eating. Int J Behav Nutr Phys Act. May 5 2017;14(1):62. doi:10.1186/s12966-017-0520-0.28476160 | Study design
921 | Wang J, Zhu D, Cheng X, Maternal perception of child weight and concern about child overweight mediates the relationship between child weight and feeding practices. Public Health Nutr. Published online January 10, 2022. doi:10.1017/S1368980022000040 | Study design
922 | Wang M, Druker S, Gapinski MA, The Role of Social Support vs. Modeling on Adolescents Diet and Physical Activity: Findings from a School-based Weight Management Trial. J Child Adolesc Behav. 2014;2(2). doi: 10.4172/2375-4494.1000132. | Intervention/exposure
923 | Wang Q, Cui S, Barnhart WR, Relationships between retrospective parental feeding practices and Chinese university students' current appetitive traits, weight status, and satisfaction with food-related life. Appetite. Apr 22 2022;175:106061. doi: 10.1016/j.appet.2022.106061.35469996 | Study design; Age of all participants at intervention/exposure
924 | Wansink B, van Kleef E. Dinner rituals that correlate with child and adult BMI. Obesity (Silver Spring). May 2014;22(5):E91–5. doi: 10.1002/oby.20629.24123987 | Study design
925 | Ward-Begnoche WL, Thompson J. Family-centered care. Assessing and surmounting barriers to eating and activity changes in overweight youth. Journal for Specialists in Pediatric Nursing. 2008;13(3):229–234. doi:10.1111/i.1744-6155.2008.00158.x.18638054 | Study design
926 | Wardle J, Sanderson S, Guthrie CA, Rapoport L, Plomin R. Parental feeding style and the intergenerational transmission of obesity risk. Obes Res. Jun 2002;10(6):453–62. doi:10.1038/oby.2002.63.12055321 | Study design
927 | Warschburger P, Kroeller K, Haerting J, Unverzagt S, van Egmond-Frohlich A. Empowering Parents of Obese Children (EPOC): A randomized controlled trial on additional long-term weighl effects of parent training. Appetite. Aug 1 2016;103:148–156. doi:10.1016/j.appet.2016.04.007.27074374 | Intervention/exposure; Health status
928 | Watson A, Dumuid D, Maher C, Parenting Styles and Their Associations With Children's Body Composition, Activity Patterns, Fitness, Diet, Health, and Academic Achievement. Child Obes. Jul 2023;19(5):316–331. doi:10.1089/chi.2022.0054.35950961 | Study design
929 | Watts AW, Barr SI, Lovato CY, Hanning RM, Masse LC. Familial Influences and their Association with the Diets of Overweight/Obese Adolescents. Canadian Journal of Diabetes. 2015;39:S32–S32. | Study design
930 | Watts AW, Loth KA, Peterson C, Boutelle KN, Neumark-Sztainer D. Characteristics of a Favorable Weight Status Change From Adolescence to Young Adulthood. J Adolesc Health. Ap 2016;58(4):403–409. doi:10.1016/j.jadohealth.2015.09.009.26552739 | Age of all participants at intervention/exposure
931 | Webber L, Cooke L, Hill C, Wardle J. Child adiposity and maternal feeding practices: a longitudinal analysis. Am J Clin Nutr. Dec 2010;92(6):1423–8. doi:10.3945/ajcn.2010.30112.20881070 | Age of all participants at intervention/exposure
932 | Wehrly SE, Bonilla C, Perez M, Liew J. Controlling parental feeding practices and child body composition in ethnically and economically diverse preschool children. Appetite. Feb 2014;73:163–71. doi:10.1016/j.appet.2013.11.009.24269508 | Study design
933 | Wen LM, Baur LA, Rissel C, Xu H, Simpson JM. Correlates of body mass index and overweight and obesity of children aged 2 years: findings from the healthy beginnings trial. Obesity (Silver Spring). Jul 2014;22(7):1723–30. doi:10.1002/oby.20700.24415528 | Age of all participants at intervention/exposure
934 | Wen LM, Taki S, Xu H, Effectiveness and co-benefits of a telephone-based intervention in reducing obesity risk of children aged 2–4 years: findings from a pragmatic randomised controlled trial during the COVID-19 pandemic in Australia. Lancet Glob Health. Mar 2023;11 Suppl 1:S13. doi:10.1016/s2214-109x(23)00096-7.36866470 | Publication status
935 | Wen LM, Xu H, Phongsavan P, Twelve-month effectiveness of telephone and SMS support to mothers with children aged 2 years in reducing children's BMI: a randomized controlled trial. Int J Obes (Lond). Apr 22 2023:1–8. doi:10.1038/s41366-023-01311-7. | Intervention/exposure; Outcome
936 | Wen LM, Xu H, Taki S, Effects of telephone support or short message service on body mass index, eating and screen time behaviours of children age 2 years: A 3-arm randomized controlled trial. Pediatr Obes. May 2022;17(5):e12875. doi:10.1111/ijpo.12875.34821063 | Intervention/exposure
937 | Wennberg M, Gustafsson PE, Wennberg P, Hammarström A. Irregular eating of meals in adolescence and the metabolic syndrome in adulthood: results from a 27-year prospective cohort. Public Health Nutr. Mar 2016;19(4):667–73. doi:10.1017/s1368980015001445.25936413 | Intervention/exposure; Outcome
938 | Werthmann J, Jansen A, Havermans R, Nederkoorn C, Kremers S, Roefs A. Bits and pieces. Food texture influences food acceptance in young children. Appetite. Jan 2015;84:181–7. doi:10.1016/j.appet.2014.09.025.25312750 | Intervention/exposure; Outcome
939 | West F, Morawska A, Joughin K. The Lifestyle Behaviour Checklist: evaluation of the factor structure. Child Care Health Dev. Jul 2010;36(4):508–15. doi:10.1111/j.1365-2214.2010.01074.x.20337641 | Study design; Intervention/exposure
940 | West F, Sanders MR, Cleghorn GJ, Davies PS. Randomised clinical trial of a family-based lifestyle intervention for childhood obesity involving parents as the exclusive agents of change. Behav Res Ther. Dec 2010;48(12):1170–9. doi:10.1016/j.brat.2010.08.008.20883981 | Intervention/exposure
941 | Whaley SE, McGregor S, Jiang L, Gomez J, Harrison G, Jenks E. A WIC-based intervention to prevent early childhood overweight. J Nutr Educ Behav. May-Jun 2010;42(3 Suppl):S47–51. doi:10.1016/j.jneb.2010.02.010.20399409 | Intervention/exposure; Outcome
942 | Whitaker RC, Deeks CM, Baughcum AE, Specker BL. The relationship of childhood adiposity to parent body mass index and eating behavior. Obes Res. May 2000;8(3):234–40. doi:10.1038/oby.2000.27.10832766 | Study design; Intervention/exposure
943 | White MA, Martin PD, Newton RL, Mediators of weight loss in a family-based intervention presented over the internet. Obes Res. Jul 2004;12(7):1050–9. doi:10.1038/oby.2004.132.15292468 | Intervention/exposure
944 | Whiteside-Mansell L, Swindle TM. Evaluation of Together We Inspire Smart Eating: pre-school fruit and vegetable consumption. Health Educ Res. 2019;34(1):62–71. doi:10.1093/her/cyy048 30590452 | Intervention/exposure; Outcome
945 | Wild CE, Rawiri NT, Willing EJ, Hofman PL, Anderson YC. Challenges of making healthy lifestyle changes for families in Aotearoa/New Zealand. Public Health Nutr. May 2021;24(7):1906–1915. doi:10.1017/s1368980020003699.33155537 | Study design
946 | Wild CEK, Wynter LE, Triggs CM, Derraik JGB, Hofman PL, Anderson YC. Five-year follow-up of a family-based multidisciplinary program for children with obesity. Obesity (Silver Spring). Sep 2021;29(9):1458–1468. doi:10.1002/oby.23225.34370401 | Intervention/exposure
947 | Wildes JE, Marcus MD, Kalarchian MA, Levine MD, Houck PR, Cheng Y. Self-reported binge eating in severe pediatric obesity: impact on weight change in a randomized controlled trial of family-based treatment. Int J Obes (Lond). Jul 2010;34(7):1143–8. doi:10.1038/ijo.2010.35.20157322 | Intervention/exposure
948 | Wilkosz ME, Chen JL, Kennedy C, Rankin S. Gender and ethnic disparities contributing to overweight in California adolescents. Z Gesundh Wiss. Apr 2010;18(2):131–144. doi:10.1007/s10389-009-0300-7.21088691 | Study design
949 | Wilksch SM, Wade TD. Risk factors for clinically significant importance of shape and weight in adolescent girls. J Abnorm Psychol. Feb 2010;119(1):206–15. doi:10.1037/a0017779.20141257 | Intervention/exposure; Outcome
950 | Williams AS, Ge B, Petroski G, Kruse RL, McElroy JA, Koopman RJ. Socioeconomic Status and Other Factors Associated with Childhood Obesity. J Am Board Fam Med. Jul-Aug 2018;31(4):514–521. doi:10.3122/jabfm.2018.04.170261.29986976 | Study design
951 | Williams KE, Hendy H, Knecht S. Parent feeding practices and child variables associated with childhood feeding problems. Journal of Developmental & Physical Disabilities. 2008;20(3):231–242. | Health status
952 | Willis TA, George J, Hunt C, Combating child obesity: impact of HENRY on parenting and family lifestyle. Pediatr Obes. Oct 2014;9(5):339–50. doi:10.1111/j.2047-6310.2013.00183.x.23818487 | Intervention/exposure; Outcome
953 | Wojcicki JM, Young MB, Perham-Hester KA, e Schweinitz P, Gessner BD. Risk factors for obesity at age 3 in Alaskan children, including the role of beverage consumption: results from Alaska PRAMS 2005–2006 and its three-year follow-up survey, CUBS, 2008–2009. PLoS One. 2015;10(3):e0118711.doi:10.1371/journal.pone.0118711.25793411 | Study design; Intervention/exposure
954 | Wolman J, Skelly E, Kolotourou M, Lawson M, Sacher P. Tackling toddler obesity through a pilot community-based family intervention. Community Pract. 2008;81(1):28–31. | Intervention/exposure
955 | Wong MS, Jones-Smith JC, Colantuoni E, Thorpe RJ, Jr B, S. N C. The Longitudinal Association Between Early Childhood Obesity and Fathers' Involvement in Caregiving and Decision-Making. Obesity (Silver Spring). Oct 2017;25(10):1754–1761. doi:10.1002/oby.21902.28634995 | Intervention/exposure; Outcome
956 | Woo JG, Guerrero ML, Ruiz-Palacios GM, Specific infant feeding practices do not consistently explain variation in anthropometry at age 1 year in urban United States, Mexico, and China cohorts. J Nutr. Feb 2013;143(2):166–74. doi:10.3945/jn.112.163857.23236024 | Intervention/exposure
957 | Wood CT, Perreira KM, Perrin EM, Confirmatory factor analysis of the Infant Feeding Styles Questionnaire in Latino families. Appetite. May 1 2016;100:118–25. doi:10.1016/j.appet.2016.02.018.26876910 | Study design; Outcome
958 | Woodruff SJ, Campbell K, Campbell T, Cole M. The associations of meals and snacks on family meals among a sample of grade 7 students from Southwestern Ontario. Appetite. Nov 2014;82:61–6. doi:10.1016/j.appet.2014.07.017.25038406 | Study design
959 | Woodruff SJ, Hanning RM, McGoldrick K, Brown KS. Healthy eating index-C is positively associated with family dinner frequency among students in grades 6–8 from Southern Ontario, Canada. Eur J Clin Nutr. May 2010;64(5):454–60. doi:10.1038/ejcn.2010.14.20197788 | Study design; Intervention/exposure
960 | Woodruff SJ, Hanning RM. Associations between family dinner frequency and specific food behaviors among grade six, seven, and eight students from Ontario and Nova Scotia. J Adolesc Health. May 2009;44(5):431–6. doi:10.1016/j.jadohealth.2008.10.141.19380089 | Study design; Intervention/exposure; Outcome
961 | Woodruff SJ, Hanning RM. Effect of meal environment on diet quality rating. Can J Diet Pract Res. Autumn 2009;70(3):118–24. doi:10.3148/70.3.2009.118. | Study design; Outcome
962 | Worobey J, Lopez MI, Hoffman DJ. Maternal behavior and infant weight gain in the first year. J Nutr Educ Behav. 2009;41(3):169–175. doi:10.1016/j.jneb.2008.06.005 19411050 | Age of all participants at intervention/exposure
963 | Worobey J, Borrelli A, Espinosa C, Worobey HS. Feeding Practices of Mothers from Varied Income and Racial/Ethnic Groups. Early Child Dev Care. Nov 1 2013;183(11):1661–1668. doi:10.1080/03004430.2012.752735.24443625 | Study design
964 | Worobey J, Peña J, Ramos I, Espinosa C. Infant difficulty and early weight gain: does fussing promote overfeeding? Matern Child Nutr. Apr 2014;10(2):295–303. doi:10.1111/j.1740-8709.2012.00410.x.22591002 | Intervention/exposure
965 | Worobey J. Early family mealtime experiences and eating attitudes in normal weight, underweight and overweight females. Eat Weight Disord. Mar 2002;7(1):39–44. doi:10.1007/bf03354428.11930984 | Study design
966 | Woźniak D, Podgórski T, Dobrzyńska M, Przysławski J, Drzymała S, Drzymała-Czyż S. The Influence of Parents' Nutritional Education Program on Their Infants' Metabolic Health. Nutrients. 2022;14(13):2671. Published 2022 Jun 28. doi:10.3390/nu14132671 35807852 | Intervention/exposure
967 | Wright AS, Reid MK, Chang SM, Walker SP. Maternal feeding styles and the risk of overweight in a cohort of Caribbean infants. Lifestyle Medicine (26883740). 2023;4(2):1–10. doi:10.1002/lim2.77. | Age of all participants at intervention/exposure
968 | Wright CM, Parkinson KN, Drewett RF. How does maternal and child feeding behavior relate to weight gain and failure to thrive? Data from a prospective birth cohort. Pediatrics. Apr 2006;117(4):1262–9. doi:10.1542/peds.2005-1215.16585323 | Age of all participants at intervention/exposure
969 | Wright J, Maher J, Tanner C. Social class, anxieties and mothers' foodwork. Sociol Health Illn. Mar 2015;37(3):422–36. doi:10.1111/1467-9566.12202.25677342 | Study design
970 | Wright JA, Phillips BD, Watson BL, Newby PK, Norman GJ, Adams WG. Randomized trial of a family-based, automated, conversational obesity treatment program for underserved populations. Obesity (Silver Spring). Sep 2013;21(9):E369–78. doi:10.1002/oby.20388.23512915 | Intervention/exposure
971 | Wrotniak BH, Epstein LH, Paluch RA, Roemmich JN. The relationship between parent and child self-reported adherence and weight loss. Obes Res. Jun 2005;13(6):1089–96. doi:10.1038/oby.2005.127.15976152 | Study design; Intervention/exposure
972 | Xu F, Marchand S, Corcoran C, A Community-Based Nutrition and Physical Activity Intervention for Children Who Are Overweight or Obese and Their Caregivers. J Obes. 2017;2017:2746595. doi:10.1155/2017/2746595.29312784 | Study design; Intervention/exposure
973 | Yamborisut U, Kosulwat V, Chittchang U, Wimonpeerapattana W, Suthutvoravut U. Factors associated with dual form of malnutrition in school children in Nakhon Pathom and Bangkok. J Med Assoc Thai. 2006;89(7):1012–1023.16881435 | Study design
974 | Yang H-M, Choo J. Effects of a parent-led childhood obesity management program for socioeconomically vulnerable families: A randomised controlled trial. Collegian. 2023;30(3):424–432. doi:10.1016/j.colegn.2022.12.002. | Intervention/exposure
975 | Young BE, Farazandeh S, Westra K, Krebs N. Maternal Beliefs Surrounding Infant Feeding, but Not Maternal BMI or Hospital Experience, Predict Breastfeeding Exclusivity and Behavior. Austin J Pediatr. 2016;3(4):1041.28553661 | Outcome
976 | Ystrom E, Barker M, Vollrath ME. Impact of mothers' negative affectivity, parental locus of control and child-feeding practices on dietary patterns of 3-year-old children: the MoBa Cohort Study. Matern Child Nutr. Jan 2012;8(1):103–14. doi:10.1111/j.1740-8709.2010.00257.x.20738782 | Study design; Outcome
977 | Yu BN, Protudjer JL, Anderson K, Fieldhouse P. Weight status and determinants of health in Manitoba children and youth. Can J Diet Pract Res. Fall 2010;71(3):115–21. doi:10.3148/71.3.2010.115. | Study design; Intervention/exposure
978 | Yuan WL, Rigal N, Monnery-Patris S, Early determinants of food liking among 5y-old children: a longitudinal study from the EDEN mother-child cohort. Int J Behav Nutr Phys Act. Feb 15 2016;13:20. doi:10.1186/s12966-016-0342-5.26876058 | Outcome
979 | Zacarías G, Shamah-Levy T, Elton-Puente E, Garbus P, García OP. Development of an intervention program to prevent childhood obesity targeted to Mexican mothers of school-aged children using intervention mapping and social cognitive theory. Eval Program Plann. Jun 2019;74:27–37. doi:10.1016/j.evalprogplan.2019.02.008.30807872 | Study design; Intervention/exposure; Outcome
980 | Zahra L, Kremer P, Bolton KA. A cross-sectional study of infant feeding practices in Vietnamese-born mothers living in Australia. BMC Pregnancy Childbirth. Dec 3 2022;22(1):895. doi:10.1186/s12884-022-05223-8.36463117 | Study design
981 | Zarychta K, Mullan B, Luszczynska A. It doesn't matter what they say, it matters how they behave: Parental influences and changes in body mass among overweight and obese adolescents. Appetite. Jan 1 2016;96:47–55. doi:10.1016/j.appet.2015.08.040.26341954 | Age of all participants at intervention/exposure
982 | Zeller MH, Reiter-Purtill J, Modi AC, Gutzwiller J, Vannatta K, Davies WH. Controlled study of critical parent and family factors in the obesigenic environment. Obesity (Silver Spring). Jan 2007;15(1):126–36. doi:10.1038/oby.2007.517.17228040 | Study design
983 | Zheng JM, Hesketh K, Bolton K, Laws R, Kremer P, Campbell K. Correlates of growth trajectories in early childhood: Results from two cohorts of Australian children. Obesity Research & Clinical Practice. 2019;13(1):111–112. doi:10.1016/j.orcp.2016.10.280. | Intervention/exposure; Publication status
984 | Zhou Z, Liew J, Yeh YC, Perez M. Appetitive Traits and Weight in Children: Evidence for Parents' Controlling Feeding Practices as Mediating Mechanisms. J Genet Psychol. Jan-Feb 2020;181(1):1–13. doi:10.1080/00221325.2019.1682506.31684838 | Study design
985 | Zhu H, Luo X, Cai T, Li Z, Liu W. Self-control and parental control mediate the relationship between negative emotions and emotional eating among adolescents. Appetite. Nov 2014;82:202–7. doi:10.1016/j.appet.2014.06.106.25084318 | Study design; Intervention/exposure
986 | Zhu Y, Ghosh D, Coffman DL, Savage JS. Estimating controlled direct effects of restrictive feeding practices in the 'Early dieting in girls' study. J R Stat Soc Ser C Appl Stat. Jan 2016;65(1):115–130. doi:10.1111/rssc.12109. | Study design
987 | Zimlich R. Helping parents--and their kids--eat better. Contemporary Pediatrics. 2020;37(11):26–27. | Publication status
988 | Zocca JM, Shomaker LB, Tanofsky-Kraff M, Links between mothers' and children's disinhibited eating and children's adiposity. Appetite. Apr 2011;56(2):324–31. doi:10.1016/j.appet.2010.12.014.21182882 | Study design; Intervention/exposure
989 | Zubatsky M. 97. Association Between Parenting Style and Adolescent Unhealthy Weight Control Behaviors. Journal of Adolescent Health. 2012;50(2):S60–S60. | Publication status