# Appendix 3 Literature search strategy

## Search A

This search was modified from an existing review^*^. It was deduplicated against the search results from the existing review prior to screening. This is reflected in the number after deduplication in the PRISMA chart. It was originally run to include children 0 to 19 years old, before the committee finalized the protocol to focus on children 2 to 6 years old.

* Spill M, Callahan E, Johns K, . Parental and Caregiver Feeding Practices and Growth, Size, and Body Composition Outcomes: A Systematic Review. April 2019. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: 10.52570/NESR.PB242018.SR0402.

### Database: PubMed

Provider: U.S. National Library of Medicine

Date(s) Searched: July 13, 2023

Dates Covered: January 1, 2000 – July 13, 2023

Table A 3 Search for PubMed

Search # | Concept | String
#1 | Caregiver Feeding | ((“Parent-Child Relations”[MeSH] OR “Parenting”[MeSH] OR “Parents”[MeSH] OR “Legal Guardians”[Mesh] OR “Grandparents”[Mesh] OR Parent[tiab] OR Parents[tiab] OR Parental[tiab] OR parenting[tiab] OR caregiver*[tiab] OR care giver*[tiab] OR maternal[tiab] OR paternal[tiab] OR mother*[tiab] OR father*[tiab] OR guardian*[tiab] OR grandparent*[tiab] OR grandmother*[tiab] OR grandfather*[tiab] OR famil*[tiab] AND (“Portion size”[MeSH] OR Style*[tiab] OR influence*[tiab] OR practice*[tiab] OR incentiv*[tiab] OR indulgen*[tiab] OR authorita*[tiab] OR reward*[tiab] OR control*[tiab] OR pressur*[tiab] OR restrict*[tiab] OR monitor*[tiab] OR respons*[tiab] OR sooth*[tiab] OR encourag*[tiab] OR discourage*[tiab] OR uninvolv*[tiab] OR disengage*[tiab] OR non-respons*[tiab] OR nonrespons*[tiab] OR force[tiab] OR forced[tiab] OR access*[tiab] OR availab*[tiab] OR behavior*[tiab] OR behaviour*[tiab] OR “laissez faire”[tiab] OR positive[tiab] OR “portion size”[tiab] OR “home Environment*”[tiab] OR “food Environment*”[tiab]) AND (“Feeding Behavior”[MeSH:NoExp] OR “Eating”[MeSH] OR “Breast Feeding”[Mesh] OR “Bottle Feeding”[Mesh] OR “breastfe*”[tiab] OR “bottlefe*”[tiab] OR Feed*[tiab] OR fed[tiab] OR eating[tiab] OR snacking[tiab] OR consum*[tiab] OR intak*[tiab] OR diet*[tiab] OR food*[tiab])) OR (“Family”[MeSH] AND “meals”[MeSH]) OR (“Family meal”[tiab:~2] OR “family dinner”[tiab:~2] OR “Family meals”[tiab:~2] OR “family dinners”[tiab:~2] OR “family mealtime”[tiab:~2])
#2 | Growth, body composition, and risk of obesity (pediatric) | “Adipose Tissue”[Mesh] OR “Body Composition”[Mesh] OR “Body Weights and Measures”[MeSH:NoExp] OR “Body Fat Distribution”[Mesh] OR “Body Mass Index”[Mesh] OR “Body Size”[Mesh] OR “Skinfold Thickness”[Mesh] OR “Waist-Hip Ratio”[Mesh] OR “Overnutrition”[Mesh] OR “Growth”[Mesh:NoExp] OR anthropometr*[tiab] OR body fat[tiab] OR fat mass[tiab] OR fat free mass[tiab] OR lean mass[tiab] OR obese[tiab] OR obesity[tiab] OR underweight[tiab] OR overweight[tiab] OR weight status[tiab] OR head circumference[tiab] OR arm circumference[tiab] OR calf circumference[tiab] OR neck circumference[tiab] OR thigh circumference[tiab] OR waist circumference[tiab] OR waist to hip ratio[tiab] OR waist hip ratio[tiab] OR body mass index[tiab] OR BMI[tiab] OR adipos*[tiab] OR body weight[tiab] OR body height[tiab] OR body size[tiab] OR body composition[tiab] OR overnutrition[tiab] OR wasting[tiab] OR healthy weight[tiab] OR skin fold[tiab] OR skin folds[tiab] OR skinfold[tiab] OR skinfolds[tiab] OR “Weight Reduction Programs”[Mesh] OR “Body-Weight Trajectory”[Mesh] OR “Weight Gain”[MeSH] OR “Weight Loss”[MeSH:NoExp] OR “Diet, Reducing”[Mesh] OR weight gain*[tiab] OR diet reduc*[tiab] OR weight cycling[tiab] OR weight decreas*[tiab] OR weight watch*[tiab] OR weight control*[tiab] OR weight retention[tiab] OR weight management[tiab] OR “maintain weight”[tiab:~4] OR “maintains weight”[tiab:~4] OR “maintaining weight”[tiab:~4] OR “maintained weight”[tiab:~4] OR “weight maintenance”[tiab:~4] OR “reduce weight”[tiab:~4] OR “reduces weight”[tiab:~4] OR “reducing weight”[tiab:~4] OR “reduced weight”[tiab:~4] OR “weight reduction”[tiab:~4] OR “lose weight”[tiab:~4] OR “loses weight”[tiab:~4] OR “losing weight”[tiab:~4] OR “lost weight”[tiab:~4] OR “weight loss”[tiab:~4] OR “change weight”[tiab:~4] OR “changes weight”[tiab:~4] OR “changing weight”[tiab:~4] OR “changed weight”[tiab:~4] OR “Growth Charts”[Mesh] OR growth chart*[tiab]OR stunting[tiab] OR stunted[tiab] OR weight for height[tiab] OR stature for age[tiab] OR weight for age[tiab] OR height for age[tiab] OR length for age[tiab] OR weight for length[tiab] OR failure to thrive[tiab]
#3 | Child 0 to 19 years old | “Infant”[MeSH] OR infant[tiab] OR newborn[tiab] OR new-born[tiab] OR neonat*[tiab] OR baby[tiab] OR babies[tiab] OR “Child”[Mesh] OR child[tiab] OR children[tiab] OR childhood[tiab] OR youth[tiab] OR youths[tiab] OR “Adolescent”[Mesh] OR adolescen*[tiab] OR teen*[tiab] OR preteen*[tiab] OR preadolescen*[tiab] OR preschool*[tiab] OR “pre-school*”[tiab] OR “Pediatrics”[Mesh] OR pediatric*[tiab] OR paediatric*[tiab] OR toddler*[tiab] OR kindergarten[tiab] OR prekindergarten[tiab] OR “pre-k”[tiab] OR boy[tiab] OR boys[tiab] OR girl[tiab] OR girls[tiab] OR schoolchild*[tiab] OR elementary[tiab] OR Primary school*[tiab] OR middle school*[tiab] OR high school*[tiab] OR highschool*[tiab] OR Secondary school*[tiab] OR pubescent[tiab] OR prepubescent[tiab] OR kid[tiab] OR kids[tiab] OR early years[tiab] OR pre-primary[tiab] OR “under five”[tiab] OR “under 5”[tiab] OR “first five years”[tiab] OR “first 5 years”[tiab] OR head start[tiab] OR Underage*[tiab] OR Juvenile*[tiab] OR Minor[tiab] OR minors[tiab] OR Young adult*[tiab] OR Young man[tiab] OR young men[tiab] OR young woman[tiab] OR young women[tiab]
#4 | | #1 AND #2 AND #3
#5 | Limits | #4 NOT (“Animals”[Mesh] NOT (“Animals”[Mesh] AND “Humans”[Mesh])) NOT (editorial[ptyp] OR comment[ptyp] OR commentary[tiab] OR news[ptyp] OR letter[ptyp] OR review[ptyp] OR systematic review[ptyp] OR systematic review[ti] OR meta-analysis[ptyp] OR meta-analysis[ti] OR meta-analyses[ti] OR protocol[ti] OR retracted publication[ptyp] OR retraction of publication[ptyp] OR retraction of publication[tiab] OR retraction notice[ti] OR “retracted publication”[ti] OR “Congress”[Publication Type] OR “Consensus Development Conference”[Publication Type] OR “conference abstract*”[tiab] OR “conference proceeding*”[tiab] OR “conference paper*”[tiab] OR “practice guideline”[ptyp] OR “practice guideline”[ti]); Filters: English, from 2000/01/01 – 3000/01/01.

### Database: Embase

Provider: Elsevier

Date(s) Searched: July 13, 2023

Dates Covered: January 1, 2000 – July 13, 2023

Table A 4 Search for Embase

Search # | Concept | String
#1 | Caregiver Feeding Practices | ((‘Child Parent Relation’/exp OR ‘Parent’/exp OR ‘Legal Guardian’/exp OR ‘Grandparent’/exp OR Parent:ab,ti OR Parents:ab,ti OR Parental:ab,ti OR parenting:ab,ti OR caregiver*:ab,ti OR ‘care giver*’:ab,ti OR maternal:ab,ti OR paternal:ab,ti OR mother*:ab,ti OR father*:ab,ti OR guardian*:ab,ti OR grandparent*:ab,ti OR grandmother*:ab,ti OR grandfather*:ab,ti OR famil*:ab,ti) AND (‘Portion size’/exp OR Style*:ab,ti OR influence*:ab,ti OR practice*:ab,ti OR incentiv*:ab,ti OR indulgen*:ab,ti OR authorita*:ab,ti OR reward*:ab,ti OR control*:ab,ti OR pressur*:ab,ti OR restrict*:ab,ti OR monitor*:ab,ti OR respons*:ab,ti OR sooth*:ab,ti OR encourag*:ab,ti OR discourage*:ab,ti OR uninvolv*:ab,ti OR disengage*:ab,ti OR ‘non-respons*’:ab,ti OR nonrespons*:ab,ti OR force:ab,ti OR forced:ab,ti OR access*:ab,ti OR availab*:ab,ti OR behavior*:ab,ti OR behaviour*:ab,ti OR ‘laissez faire’:ab,ti OR positive:ab,ti OR ‘portion size’:ab,ti OR ‘home Environment*’:ab,ti OR ‘food Environment*’:ab,ti) AND (‘Feeding Behavior’/de OR ‘Eating’/exp OR ‘breast feeding’/exp OR ‘bottle feeding’/exp OR breastfe*:ab,ti OR bottlefe*:ab,ti OR Feed*:ab,ti OR fed:ab,ti OR eating:ab,ti OR snacking:ab,ti OR consum*:ab,ti OR intak*:ab,ti OR diet*:ab,ti OR food*:ab,ti)) OR ('family'/exp AND 'meals'/exp) OR (family NEAR/3 (meal* OR dinner*)):ab,ti
#2 | Growth, body composition, and risk of obesity (pediatric) | ‘adipose tissue’/exp OR ‘body composition’/exp OR ‘anthropometry’/de OR ‘body mass’/exp OR ‘anthropometric parameters’/exp OR ‘skinfold thickness’/exp OR ‘overnutrition’/exp OR ‘growth’/de OR ‘anthropometr*’:ab,ti OR ‘body fat’:ab,ti OR ‘fat mass’:ab,ti OR ‘fat free mass’:ab,ti OR ‘lean mass’:ab,ti OR ‘obese’:ab,ti OR ‘obesity’:ab,ti OR ‘underweight’:ab,ti OR ‘overweight’:ab,ti OR ‘weight status’:ab,ti OR ‘head circumference’:ab,ti OR ‘arm circumference’:ab,ti OR ‘calf circumference’:ab,ti OR ‘neck circumference’:ab,ti OR ‘thigh circumference’:ab,ti OR ‘waist circumference’:ab,ti OR ‘waist to hip ratio’:ab,ti OR ‘waist hip ratio’:ab,ti OR ‘body mass index’:ab,ti OR ‘BMI’:ab,ti OR ‘adipos*’:ab,ti OR ‘body weight’:ab,ti OR ‘body height’:ab,ti OR ‘body size’:ab,ti OR ‘body composition’:ab,ti OR ‘overnutrition’:ab,ti OR ‘wasting’:ab,ti OR ‘healthy weight’:ab,ti OR ‘skin fold*’:ab,ti OR ‘skinfold*’:ab,ti OR ‘body weight management’/exp OR ‘body weight change’/exp OR ‘weight gain*’:ab,ti OR ‘diet reduc*’:ab,ti OR ‘weight cycling’:ab,ti OR ‘weight watch*’:ab,ti OR ‘weight control*’:ab,ti OR ‘weight retention’:ab,ti OR ‘weight management’:ab,ti OR (weight NEAR/4 (decreas* OR gain* OR maint* OR reduc* OR loss* OR chang*)):ab,ti OR ‘weight chart’/exp OR ‘growth chart*’:ab,ti OR stunting:ab,ti OR stunted:ab,ti OR ‘weight for height’:ab,ti OR ‘stature for age’:ab,ti OR ‘weight for age’:ab,ti OR ‘height for age’:ab,ti OR ‘length for age’:ab,ti OR ‘weight for length’:ab,ti OR ‘ failure to thrive’:ab,ti
#3 | Child 0 to 19 years old | 'child'/exp OR infant:ab,ti OR newborn:ab,ti OR 'new-born':ab,ti OR neonat*:ab,ti OR baby:ab,ti OR babies:ab,ti OR child:ab,ti OR children:ab,ti OR childhood:ab,ti OR youth:ab,ti OR youths:ab,ti OR 'adolescent'/exp OR adolescen*:ab,ti OR teen*:ab,ti OR preteen*:ab,ti OR preadolescen*:ab,ti OR preschool*:ab,ti OR 'pre-school*':ab,ti OR 'pediatrics'/exp OR pediatric*:ab,ti OR paediatric*:ab,ti OR toddler*:ab,ti OR kindergarten:ab,ti OR prekindergarten:ab,ti OR 'pre-k':ab,ti OR boy:ab,ti OR boys:ab,ti OR girl:ab,ti OR girls:ab,ti OR schoolchild*:ab,ti OR elementary:ab,ti OR 'primary school*':ab,ti OR 'middle school*':ab,ti OR 'high and school*':ab,ti OR highschool*:ab,ti OR 'secondary school*':ab,ti OR pubescent:ab,ti OR prepubescent:ab,ti OR kid:ab,ti OR kids:ab,ti OR 'early years':ab,ti OR 'pre-primary':ab,ti OR 'under five*':ab,ti OR 'under 5':ab,ti OR 'first five years':ab,ti OR 'first 5 years':ab,ti OR 'head start':ab,ti OR underage*:ab,ti OR juvenile*:ab,ti OR minor:ab,ti OR minors:ab,ti OR 'young adult*':ab,ti OR 'young man':ab,ti OR 'young men':ab,ti OR 'young woman':ab,ti OR 'young women':ab,ti
#4 | | #1 AND #2 AND #3
#5 | Limits | #4 AND ([article]/lim OR [article in press]/lim) NOT ([animals]/lim NOT ([animals]/lim AND [humans]/lim)) AND [english]/lim NOT ([conference abstract]/lim OR [conference paper]/lim OR [conference review]/lim OR [editorial]/lim OR [erratum]/lim OR [letter]/lim OR [note]/lim OR 'retraction of publication':ab,ti OR 'retraction notice':ti OR 'retracted publication':ab,ti OR [review]/lim OR [systematic review]/lim OR [meta analysis]/lim OR 'practice guideline':ti OR 'protocol':ti) AND [2000–2023]/py

### Database: Cochrane Central Register of Controlled Trials (CENTRAL)

Provider: John Wiley & Sons

Date(s) Searched: July 13, 2023

Dates Covered: January 1, 2000 – July 13, 2023

Table A 5 Search for Cochrane CENTRAL

Search # | Concept | String
#1 | Caregiver Feeding Practices | (([mh "Parent-Child Relations"] OR [mh "Parenting"] OR [mh "Legal Guardians"] OR [MH "Grandparents"] OR (Parent OR Parents OR Parental OR parenting OR caregiver* OR care giver* OR maternal OR paternal OR mother* OR father* OR guardian* OR grandparent* OR grandmother* OR grandfather* OR famil*):ti,ab,kw) AND ([MH “Portion size”] OR (Style* OR influence* OR practice* OR incentiv* OR indulgen* OR authorita* OR reward* OR control* OR pressur* OR restrict* OR monitor* OR respons* OR sooth* OR encourag* OR discourage* OR uninvolv* OR disengage* OR (non NEXT respons*) OR nonrespons* OR force OR forced OR access* OR availab* OR behavior* OR behaviour* OR “laissez faire” OR positive OR “portion size” OR (home NEXT Environment*) OR (food NEXT Environment*)):ti,ab,kw) AND ([mh ^"Feeding Behavior"] OR [mh "Eating"] OR [mh "Breast Feeding"] OR [mh "Bottle Feeding"] OR (breastfe* OR bottlefe* OR Feed* OR fed OR eating OR snacking OR consum* OR intak* OR diet* OR food*):ti,ab,kw)) OR ([mh “Family”] AND [mh “meals”]) OR (family NEAR/3 (meal* OR dinner*)):ti,ab,kw
#2 | Growth, body composition, and risk of obesity (pediatric) | ([mh "Adipose Tissue"] OR [mh "Body Composition"] OR [mh ^"Body Weights and Measures"] OR [mh "Body Fat Distribution"] OR [mh "Body Mass Index"] OR [mh "Body Size"] OR [mh "Skinfold Thickness"] OR [mh "Waist-Hip Ratio"] OR [mh Overnutrition] OR [mh ^Growth] OR anthropometr* OR “body fat” OR “fat mass” OR “fat free mass” OR “lean mass” OR obese OR obesity OR underweight OR overweight OR “weight status” OR “head circumference” OR “arm circumference” OR “calf circumference” OR “neck circumference” OR “thigh circumference” OR “waist circumference” OR “waist to hip ratio” OR “waist hip ratio” OR “body mass index” OR BMI OR adipos* OR “body weight” OR “body height” OR “body size” OR “body composition” OR overnutrition OR wasting OR “healthy weight” OR “skin fold” OR “skin folds” OR skinfold OR skinfolds):ti,ab,kw OR ([mh "Weight Reduction Programs"] OR [mh "Body-Weight Trajectory"] OR [mh "Weight Gain"] OR [mh ^“Weight Loss”] OR [mh "Diet, Reducing"] OR “diet reduc*” OR “weight cycling” OR “weight watch*” OR “weight control*” OR “weight retention” OR “weight management”):ti,ab,kw OR ((weight NEAR/4 (decreas* OR gain* OR maint* OR reduc* OR loss* OR chang*)) OR [mh “Growth Charts”] OR “growth chart*” OR stunting OR stunted OR “weight for height” OR “stature for age” OR “weight for age” OR “height for age” OR “length for age” OR “weight for length” OR “failure to thrive”):ti,ab,kw
#3 | Child 0 to 19 years old | [mh “Infant”] OR [mh "Child"] OR [mh "Adolescent"] OR [mh "Pediatrics"] OR (infant OR newborn OR "new-born" OR neonat* OR baby OR babies OR child OR children OR childhood OR youth OR youths OR adolescen* OR teen* OR preteen* OR preadolescen* OR preschool* OR “pre-school” OR “pre-schools” OR “pre schooler” OR “preschoolers” OR pediatric* OR paediatric* OR toddler* OR kindergarten OR prekindergarten OR “pre-k” OR boy OR boys OR girl OR girls OR schoolchild* OR elementary OR “Primary school” OR “primary schools” OR “primary schooler” OR “primary schoolers” OR “middle school” OR “middle schools” OR “middle schooler” OR “middle schoolers” OR “high school” OR “high schools” OR “high schooler” OR “high schoolers” OR highschool* OR “Secondary school” OR “secondary schools” OR “secondary schooler” OR “secondary schoolers” OR pubescent OR prepubescent OR kid OR kids OR “early years” OR “pre-primary” OR “under five” OR “under 5” OR “first five years” OR “first 5 years” OR “head start” OR Underage* OR Juvenile* OR Minor OR minors OR “Young adult” OR “young adults” OR “Young man” OR “young men” OR “young woman” OR “young women”):ti,ab,kw
#4 | | #1 AND #2 AND #3; In Trials. Word variations have been searched.; Year First published: 2000–2023

### Database: CINAHL

Provider: EBSCO

Date(s) Searched: July 13, 2023

Dates Covered: January 1, 2000 – July 13, 2023

Table A 6 Search for CINAHL

Search # | Concept | String
#1 | Caregiver Feeding Practices | (((MH “Parent-Child Relations+”) OR (MH “Parenting+”) OR (MH “Parents+”) OR (MH “Guardianship, Legal”+) OR (MH “Grandparents”) OR AB (parent OR parents OR parental OR parenting OR caregiver* OR maternal OR paternal OR mother* OR father* OR guardian* OR grandparent* OR grandmother* OR grandfather* OR famil*) OR TI (parent OR parents OR parental OR parenting OR caregiver* OR maternal OR paternal OR mother* OR father* OR guardian* OR grandparent* OR grandmother* OR grandfather* OR famil*)) AND ((MH “Portion size”) OR AB (Style* OR influence* OR practice* OR incentiv* OR indulgen* OR authorita* OR reward* OR control* OR pressur* OR restrict* OR monitor* OR respons* OR sooth* OR encourag* OR discourage* OR uninvolv* OR disengage* OR “non-respons*” OR nonrespons* OR force OR forced OR access* OR availab* OR behavior* OR behaviour* OR “laissez faire” OR positive OR “portion size” OR “home Environment*” OR “food Environment*”) OR TI (Style* OR influence* OR practice* OR incentiv* OR indulgen* OR authorita* OR reward* OR control* OR pressur* OR restrict* OR monitor* OR respons* OR sooth* OR encourag* OR discourage* OR uninvolv* OR disengage* OR “non-respons*” OR nonrespons* OR force OR forced OR access* OR availab* OR behavior* OR behaviour* OR “laissez faire” OR positive OR “portion size” OR “home Environment*” OR “food Environment*”)) AND ((MH “Eating Behavior”) OR (MH “Eating”) OR (MH “Breast Feeding”) OR (MH “Bottle Feeding”) OR AB (“breastfe*" OR “bottlefe*” OR Feed* OR fed OR eating OR snacking OR consum* OR intak* OR diet* OR food*) OR TI (“breastfe*” OR “bottlefe*” OR Feed* OR fed OR eating OR snacking OR consum* OR intak* OR diet* OR food*))) OR ((MH “Family”) AND (MH “Meals”)) OR (AB (family N3 (meal* OR dinner*)) OR TI (family N3 (meal* OR dinner*)))
#2 | Growth, body composition, and risk of obesity (pediatric) | (MH “Adipose Tissue+”) OR (MH “Body Composition+”) OR (MH “Body Weights and Measures”) OR (MH “Arm Circumference”) OR (MH “Body Height”) OR (MH “Body Mass Index”) OR (MH “Body Size”) OR (MH “Body Weight+”) OR (MH “Crown-Rump Length”) OR (MH “Waist Circumference”) OR (MH “Waist-Hip Ratio”) OR (MH “Skinfold Thickness”) OR (MH “Obesity+”) OR (MH “Overnutrition”) OR (MH “Growth”) OR (TI anthropometr* OR “body fat” OR “fat mass” OR “fat free mass” OR “lean mass” OR obese OR obesity OR underweight OR overweight OR “weight status” OR “head circumference” OR “arm circumference” OR “calf circumference” OR “neck circumference” OR “thigh circumference” OR “waist circumference” OR “waist to hip ratio” OR “waist hip ratio” OR “body mass index” OR BMI OR adipos* OR “body weight” OR “body height” OR “body size” OR “body composition” OR overnutrition OR wasting OR “healthy weight” OR “skin fold” OR “skin folds” OR skinfold OR skinfolds) OR (AB anthropometr* OR “body fat” OR “fat mass” OR “fat free mass” OR “lean mass” OR obese OR obesity OR underweight OR overweight OR “weight status” OR “head circumference” OR “arm circumference” OR “calf circumference” OR “neck circumference” OR “thigh circumference” OR “waist circumference” OR “waist to hip ratio” OR “waist hip ratio” OR “body mass index” OR BMI OR adipos* OR “body weight” OR “body height” OR “body size” OR “body composition” OR overnutrition OR wasting OR “healthy weight” OR “skin fold” OR “skin folds” OR skinfold OR skinfolds) OR (MH “Weight Reduction Programs”) OR (MH “Body Weight Changes”) OR (MH “Weight Gain+”) OR (MH “Weight Loss”) OR (MH “Diet, Reducing”) OR (TI “diet reduc*” OR “weight cycling” OR “weight watch*” OR “weight control*” OR “weight retention” OR “weight management”) OR (AB “diet reduc*” OR “weight cycling” OR “weight watch*” OR “weight control*” OR “weight retention” OR “weight management”) OR (TI (weight N4 (decreas* OR gain* OR maint* OR reduc* OR loss* OR chang*))) OR (AB (weight N4 (decreas* OR gain* OR maint* OR reduc* OR loss* OR chang*))) OR TI (“growth chart*” OR stunting OR stunted OR “weight for height” OR “stature for age” OR “weight for age” OR “height for age” OR “length for age” OR “weight for length” OR “failure to thrive”) OR AB (“growth chart*” OR stunting OR stunted OR “weight for height” OR “stature for age” OR “weight for age” OR “height for age” OR “length for age” OR “weight for length” OR “failure to thrive”)
#3 | Child 0 to 19 years old | (MH “Child+”) OR (MH “Adolescence+”) OR (MH “Pediatrics+”) OR AB (infant OR newborn OR new-born OR neonat* OR baby OR babies OR child OR children OR childhood OR youth OR youths OR adolescen* OR teen* OR preteen* OR preadolescen* OR preschool* OR “pre-school*” OR pediatric* OR paediatric* OR toddler* OR kindergarten OR prekindergarten OR “pre-k” OR boy OR boys OR girl OR girls OR schoolchild* OR elementary OR “Primary school*” OR “middle school*” OR “high school*” OR highschool* OR “Secondary school*” OR pubescent OR prepubescent OR kid OR kids OR “early years” OR “pre-primary” OR “under five” OR “under 5” OR “first five years” OR “first 5 years” OR “head start” OR Underage* OR Juvenile* OR Minor OR minors OR “Young adult*” OR “Young man” OR “young men” OR “young woman” OR “young women”) OR TI (infant OR newborn OR new-born OR neonat* OR baby OR babies OR child OR children OR childhood OR youth OR youths OR adolescen* OR teen* OR preteen* OR preadolescen* OR preschool* OR “pre-school*” OR pediatric* OR paediatric* OR toddler* OR kindergarten OR prekindergarten OR “pre-k” OR boy OR boys OR girl OR girls OR schoolchild* OR elementary OR “Primary school*” OR “middle school*” OR “high school*” OR highschool* OR “Secondary school*” OR pubescent OR prepubescent OR kid OR kids OR “early years” OR “pre-primary” OR “under five” OR “under 5” OR “first five years” OR “first 5 years” OR “head start” OR Underage* OR Juvenile* OR Minor OR minors OR “Young adult*” OR “Young man” OR “young men” OR “young woman” OR “young women”)
#4 | | S1 AND S2 AND S3
#5 | Limits | S4 NOT ((MH “Animals+”) OR (MH “Animal Studies”)) NOT ((MH “Literature Review”) OR (MH “Meta Analysis”) OR (MH “Systematic Review”) OR (MH “News”) OR (MH “Retracted Publication”) OR (MH “Retraction of Publication)); Published Date: 20000101–20230713; Limiters - English Language, Expanders - Apply equivalent subject