# Appendix 2 Conclusion statements from the existing systematic review

Table A 2 Conclusion statements from the existing systematic review for the research question: What is the relationship between caregiver feeding practices and growth, body composition and risk of obesity?

Citation | Conclusion statement and grade
Spill M, Callahan E, Johns K, Shapiro M, Spahn JM, Wong YP, Terry N, Benjamin-Neelon S, Birch L, Black M, Briefel R, Cook J, Faith M, Mennella J, Casavale KO, Stoody E. Parental and Caregiver Feeding Practices and Growth, Size, and Body Composition Outcomes: A Systematic Review. April 2019. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: 10.52570/NESR.PB242018.SR0402. | Moderate evidence from randomized controlled trials suggests that providing responsive feeding guidance to mothers to recognize and respond appropriately to a child’s hunger and satiety cues can contribute to “normal” weight gain and/or “normal” weight status in children two years and younger compared to children whose mothers did not receive responsive feeding guidance. (Grade: Moderate); Moderate evidence from longitudinal cohort studies indicates an association between maternal feeding practices and the child’s weight status and/or weight gain, but the direction of effect has not been adequately studied. Restrictive feeding practices are associated with increased weight gain and higher weight status and pressuring feeding practices are associated with decreased weight gain and lower weight status. Evidence suggests mothers' feeding practices are related to concerns about children’s body weight. (Grade. Moderate)