# Appendix 1 Abbreviations

Table A 1 List of abbreviations
Abbreviation: Full name
BMI: Body Mass Index
GBCO: Growth, Body Composition and Risk of Obesity
HHS: United States Department of Health and Human Services
NESR: Nutrition Evidence Systematic Review
PCS: Prospective Cohort Study
SEP: Socioeconomic Position
USDA: United States Department of Agriculture