# References of the articles included in the systematic review

1 Amaro-Rivera K, Molina J, Perez CM, Palacios C. Longitudinal Associations between Dietary Patterns and Weight Status in Puerto Rican Infants and Toddlers' Participants of the WIC Program. P R Health Sci J. Jun 2019;38(2):75–80.31260549
2 Ay L, Hokken-Koelega AC, Mook-Kanamori DO, Tracking and determinants of subcutaneous fat mass in early childhood: the Generation R Study. Int J Obes. Jul 2008;32(7):1050–9. doi:10.1038/ijo.2008.76.
3 Carruth BR, Skinner JD, Houck KS, Moran JD. Addition of supplementary foods and infant growth (2 to 24 months). J Am Coll Nutr. Jun 2000;19(3):405–12. doi:10.1080/07315724.2000.10718937 10872903
4 Gingras V, Aris IM, Rifas-Shiman SL, Switkowski KM, Oken E, Hivert MF. Timing of Complementary Feeding Introduction and Adiposity Throughout Childhood. Pediatrics. Dec 2019;144(6):e20191320. doi:10.1542/peds.2019-1320 31757860
5 Schack-Nielsen L, Sorensen T, Mortensen EL, Michaelsen KF. Late introduction of complementary feeding, rather than duration of breastfeeding, may protect against adult overweight. Am J Clin Nutr. Mar 2010;91:619–27. doi:10.3945/ajcn.2008.27078 20032492
6 Au LE, Arnold CD, Ritchie LD, Frongillo EA. The Infant Diet Quality Index Predicts Dietary and Adiposity Outcomes in US Children 2 to 4 years old. J Nutr. 2023;153:741–8. doi:10.1016/j.tjnut.2023.01.037 36806452
7 D'Hollander CJ, Keown-Stoneman CDG, Birken CS, Timing of Introduction to Solid Food, Growth, and Nutrition Risk in Later Childhood. Article in Press. J Pediatr. 2022;240:102–109.e3. doi:10.1016/j.jpeds.2021.08.076 34481809
8 Woo JG, Guerrero ML, Ruiz-Palacios GM, Specific infant feeding practices do not consistently explain variation in anthropometry at age 1 year in urban United States, Mexico, and China cohorts. J Nutr. Feb 2013;143(2):166–74. doi:10.3945/jn.112.163857 23236024
9 Choudhary D, Rideout TC, Cameron CE, Egg Introduction during Infancy is Associated with Lower Fat Mass Index in Females at Early Adolescence. J Nutr. 2023;153(1):158–166. doi:10.1016/j.tjnut.2022.11.003 36913449
10 Mi B, Liu H, Wang Y, Infant age at egg introduction and malnutrition-related child growth in the United States. Article. Matern Child Nutr. 2022;18(4):e13390. doi:10.1111/mcn.13390 35712809
11 Burke V, Beilin LJ, Simmer K, Predictors of body mass index and associations with cardiovascular risk factors in Australian children: a prospective cohort study. Int J Obes. Jan 2005;29(1):15–23. doi:10.1038/sj.ijo.0802750
12 Butte NF, Wong WW, Hopkinson JM, Smith EO, Ellis KJ. Infant feeding mode affects early growth and body composition. Pediatrics. Dec 2000;106:1355–66. doi:10.1542/peds.106.6.1355 11099589
13 Ejlerskov KT, Christensen LB, Ritz C, Jensen SM, Molgaard C, Michaelsen KF. The impact of early growth patterns and infant feeding on body composition at 3 years of age. Br J Nutr. Jul 2015;114(2):316–27. doi:10.1017/S0007114515001427 26131962
14 Farris RP, Frank GC, Webber LS, Srinivasan SR, Berenson GS. Influence of milk source on serum lipids and lipoproteins during the first year of life, Bogalusa heart study. Am J Clin Nutr. Jan 1982;35(1):42–9. doi:10.1093/ajcn/35.1.42 7064877
15 Flores G, Lin H. Factors predicting overweight in US kindergartners. Am J Clin Nutr. Jun 2013;97(6):1178–87. doi:10.3945/ajcn.112.052019.23553169
16 Flores G, Lin H. Factors predicting severe childhood obesity in kindergarteners. Int J Obes. Jan 2013;37(1):31–9. doi:10.1038/ijo.2012.168
17 Kuperberg K, Evers S. Feeding patterns and weight among First Nations children. Can J Diet Pract Res. Summer 2006;67(2):79–84. doi:10.3148/67.2.2006.79 16759434
18 Retamal R, Mascie-Taylor CGN, Villegas R, Rodriguez-Osiac L. Relationship between age at giving fortified powdered cow's milk and cessation of breastfeeding on the nutritional status of a Chilean child cohort followed from birth to 3 years of age. Eur J Clin Nutr. Jul 2020;74(7):1022–1028. doi:10.1038/s41430-020-0665-9 32457472
19 Rossiter MD, Evers SE. Infant feeding practices and children's weight status. Can J Diet Pract Res. Fall 2013;74(3):107–13. doi:10.3148/74.3.2013.107 24018001
20 Soczynska I, Dai D, O'Connor DL, Birken CS, Maguire JL. Age of cow milk introduction and growth among 3–5-year-old children. Public Health Nutr. Jul 29 2021;24:5436–42. doi:10.1017/S1368980020001925 32723404
21 Becker PC, Neves RO, Silva CHD, Goldani MZ, Bernardi JR. Does early fruit juice introduction influence anthropometric outcomes and food consumption at preschool age? Cien Saude Colet. 2023;28(1):269–280. doi:10.1590/1413-81232023281.09992022 36629571
22 Cantoral A, Tellez-Rojo MM, Ettinger AS, Hu H, Hernandez-Avila M, Peterson K. Early introduction and cumulative consumption of sugar-sweetened beverages during the pre-school period and risk of obesity at 8–14 years of age. Pediatr Obes. Feb 2016;11(1):68–74. doi:10.1111/ijpo.12023 25891908
23 Pan L, Li R, Park S, Galuska DA, Sherry B, Freedman DS. A longitudinal analysis of sugar-sweetened beverage intake in infancy and obesity at 6 years. Pediatrics. Sep 2014;134 Suppl 1:S29–35. doi:10.1542/peds.2014-0646F 25183752
24 Robinson SL, Sundaram R, Lin TC, Age of Juice Introduction and Child Anthropometry at 2–3 and 7–9 Years. J Pediatr. 2022;245:135–41.e1. doi:10.1016/j.jpeds.2022.02.019 35182582
25 Santorelli G, Fairley L, Petherick ES, Cabieses B, Sahota P. Ethnic differences in infant feeding practices and their relationship with BMI at 3 years of age - results from the Born in Bradford birth cohort study. Br J Nutr. May 28 2014;111(10):1891–7. doi:10.1017/S0007114514000099 24513174
26 Gaffney KF, Kitsantas P, Cheema J. Clinical practice guidelines for feeding behaviors and weight-for-age at 12 months: a secondary analysis of the Infant Feeding Practices Study II. Worldviews Evid Based Nurs. Dec 2012;9(4):234–42. doi:10.1111/j.1741-6787.2011.00236.x.22233459
27 Mahoney S, Bryant M, Sahota P, Barber S. Dietary intake in the early years and its relationship to BMI in a bi-ethnic group: the Born in Bradford 1000 study. Article. Public Health Nutr. 2018;21(12):2242–2254. doi:10.1017/S1368980018000654 29607793
28 VandyousefiS, Davis JN, Gunderson EP. Association of infant diet with subsequent obesity at 2–5 years among children exposed to gestational diabetes: the SWIFT study. Diabetologia. May 2021;64(5):1121–1132. doi:10.1007/s00125-020-05379-y 33495846
29 Garden FL, Marks GB, Simpson JM, Webb KL. Body mass index (BMI) trajectories from birth to 11.5 years: relation to early life food intake. Nutrients. Oct 2012;4(10):1382–98. doi:10.3390/nu4101382.23201761
30 Garden FL, Marks GB, Almqvist C, Simpson JM, Webb KL. Infant and early childhood dietary predictors of overweight at age 8 years in the CAPS population. Eur J Clin Nutr. Apr 2011;65(4):454–62. doi:10.1038/ejcn.2011.7 21346718
31 Jin H, Shan T, Li S, Association of infant feeding patterns with body fat mass and obesity in the first 2 years of life: a longitudinal twin birth cohort study. Int J Food Sci Nutr. Aug 19 2022;73:263–273. doi:10.1080/09637486.2021.1968357 34412548
32 Almquist-Tangen G, Dahlgren J, Roswall J, Bergman S, Alm B. Milk cereal drink increases BMI risk at 12 and 18 months, but formula does not. Acta Paediatr. Dec 2013;102(12):1174–9. doi:10.1111/apa.12418.24028671
33 Almquist-Tangen G, Bergman S, Dahlgren J, Lindholm A, Roswall J, Alm B. Consuming milk cereal drinks at one year of age was associated with a twofold risk of being overweight at the age of five. Article. Acta Paediatr. 2019;108(6):1115–1121. doi:10.1111/apa.14666 30511422
34 Gaffney KF, Kitsantas P, Brito A, Swamidoss CS. Postpartum depression, infant feeding practices, and infant weight gain at six months of age. J Pediatr Health Care. Jan-Feb 2014;28(1):43–50. doi:10.1016/j.pedhc.2012.10.005 23266435
35 Krebs NF, Westcott JE, Butler N, Robinson C, Bell M, Hambidge KM. Meat as a first complementary food for breastfed infants: feasibility and impact on zinc intake and status. J Pediatr Gastroenterol Nutr. Feb 2006;42(2):207–14. doi:10.1097/01.mpg.0000189346.25172.fd 16456417
36 Lande B, Andersen LF, Henriksen T, Relations between high ponderal index at birth, feeding practices and body mass index in infancy. Eur J Clin Nutr. Nov 2005;59(11):1241–9. doi:10.1038/sj.ejcn.1602235 16106264
37 Lindholm A, Bergman S, Alm B, Nutrition- and feeding practice-related risk factors for rapid weight gain during the first year of life: a population-based birth cohort study. BMC Pediatr. Nov 5 2020;20(1):507. doi:10.1186/s12887-020-02391-4 33148198
38 Lundkvist E, Stoltz Sjostrom E, Lundberg R, Silfverdal SA, West CE, Domellof M. Fruit Pouch Consumption and Dietary Patterns Related to BMIz at 18 Months of Age. Nutrients. Jun 30 2021;13(7):2265. doi:10.3390/nu13072265 34208982
39 Ma J, Sun Q, Liu J, The Effect of Iron Fortification on Iron (Fe) Status and Inflammation: A Randomized Controlled Trial. PloS one. 2016;11(12):e0167458. doi:10.1371/journal.pone.0167458 27923057
40 Moore AM, Vadiveloo M, Tovar A, McCurdy K, Ostbye T, Benjamin-Neelon SE. Associations of Less Healthy Snack Food Consumption with Infant Weight-for-Length Z-Score Trajectories: Findings from the Nurture Cohort Study. Nutrients. Nov 13 2019;11(11):2752. doi:10.3390/nu11112752 31766167
41 Tang M, Sheng XY, Krebs NF, Hambidge KM. Meat as complementary food for older breastfed infants and toddlers: a randomized, controlled trial in rural China. Food Nutr Bull. Dec 2014;35(4 Suppl):S188–92. doi:10.1177/15648265140354S304 25639137
42 Ventura AK, Thompson K. Predictors of Resilience Among Infants at Risk for Rapid Weight Gain. Obesity. Jan 2019;27(1):130–136. doi:10.1002/oby.22351 30569642
43 Duchen K, Olsen Faresjo A, Klingberg S, Faresjo T, Ludvigsson J. Fatty fish intake in mothers during pregnancy and in their children in relation to the development of obesity and overweight in childhood: The prospective ABIS study. Article. Obes Sci Pract. 2020;6(1):57–69. doi:10.1002/osp4.377 32128243
44 Morgan J, Taylor A, Fewtrell M. Meat consumption is positively associated with psychomotor outcome in children up to 24 months of age. J Pediatr Gastroenterol Nutr. Nov 2004;39(5):493–8. doi:10.1097/00005176-200411000-00009 15572888
45 Smith-Brown P, Morrison M, Krause L, Newby R, Davies PS. Growth and protein-rich food intake in infancy is associated with fat-free mass index at 2–3 years of age. J Paediatr Child Health. Jul 2018;54(7):770–775. doi:10.1111/jpc.13863 29493037
46 Tang M, Andersen V, Hendricks AE, Krebs NF. Different Growth Patterns Persist at 24 Months of Age in Formula-Fed Infants Randomized to Consume a Meat- or Dairy-Based Complementary Diet from 5 to 12 Months of Age. J Pediatr. Mar 2019;206:78–82. doi:10.1016/j.jpeds.2018.10.020 30413312
47 Tang M, Hendricks AE, Krebs NF. A meat- or dairy-based complementary diet leads to distinct growth patterns in formula-fed infants: a randomized controlled trial. Am J Clin Nutr. May 1 2018;107(5):734–742. doi:10.1093/ajcn/nqy038 29722841
48 Friel JK, Andrews WL, Edgecombe C, Eighteen-month follow-up of infants fed evaporated milk formula. Article. Can J Public Health. 1999;90(4):240–243. doi:10.1007/BF03404124 10489720
49 Friel JK, Andrews WL, Simmons BS, Evaluation of full-term infants fed an evaporated milk formula. Article. Acta Paediatr. 1997;86(5):448–453. doi:10.1111/j.1651-2227.1997.tb08910.x 9183479
50 Goh EK, Kim OY, Yoon SR, Jeon HJ. Timing of Adiposity Rebound and Determinants of Early Adiposity Rebound in Korean Infants and Children Based on Data from the National Health Insurance Service. Article. Nutrients. 2022;14(5):929. doi:10.3390/nu14050929 35267902
51 Hopkins D, Steer CD, Northstone K, Emmett PM. Effects on childhood body habitus of feeding large volumes of cow or formula milk compared with breastfeeding in the latter part of infancy. Am J Clin Nutr. Nov 2015;102(5):1096–103. doi:10.3945/ajcn.114.100529 26354544
52 Larnkjaer A, Hoppe C, Mølgaard C, Michaelsen KF. The effects of whole milk and infant formula on growth and IGF-I in late infancy. Eur J Clin Nutr. Aug 2009;63(8):956–63. doi:10.1038/ejcn.2008.80 19174829
53 Thorisdottir B, Gunnarsdottir I, Thorisdottir AV, Palsson GI, Halldorsson TI, Thorsdottir I. Nutrient intake in infancy and body mass index at six years in two population-based cohorts recruited before and after revision of infant dietary recommendations. Ann Nutr Metab. 2013;63(1–2):145–51. doi:10.1159/000354431 23988865
54 Wall CR, Hill RJ, Lovell AL, A multicenter, double-blind, randomized, placebo-controlled trial to evaluate the effect of consuming Growing Up Milk "lite" on body composition in children aged 12–23 mo. Article. Am J Clin Nutr. 2019;109(3):576–85. doi:10.1093/ajcn/nqy302 30831579
55 Wosje KS, Specker BL, Giddens J. No differences in growth or body composition from age 12 to 24 months between toddlers consuming 2% milk and toddlers consuming whole milk. J Am Diet Assoc. Jan 2001;101(1):53–6. doi:10.1016/S0002-8223(01)00015-3 11209585
56 Chaidez V, McNiven S, Vosti SA, Kaiser LL. Sweetened food purchases and indulgent feeding are associated with increased toddler anthropometry. J Nutr Educ Behav. Jul-Aug 2014;46(4):293–298. doi:10.1016/j.jneb.2013.05.011 24188800
57 Hwang IT, Ju YS, Lee HJ, Shim YS, Jeong HR, Kang MJ. Body mass index trajectories and adiposity rebound during the first 6 years in Korean children: Based on the National Health Information Database, 2008–2015. PloS one. 2020;15(10):e0232810. doi:10.1371/journal.pone.0232810 33125366
58 Leermakers ET, Felix JF, Erler NS, Sugar-containing beverage intake in toddlers and body composition up to age 6 years: the Generation R study. Eur J Clin Nutr. Mar 2015;69(3):314–21. doi:10.1038/ejcn.2015.2 25649238
59 Leermakers ET, Felix JF, Jaddoe VW, Raat H, Franco OH, Kiefte-de Jong JC. Sugar-containing beverage intake at the age of 1 year and cardiometabolic health at the age of 6 years: the Generation R Study. Int J Behav Nutr Phys Act. Sep 17 2015;12:114. doi:10.1186/s12966-015-0278-1 26377916
60 Lewis KH, Skelton J, Hsu F, Ezouah P, Taveras EM, Block JP. Use of Electronic Health Record Data to Study the Association of Sugary Drink Consumption With Child Weight Status. Acad Pediatr. 2020;20(6):767–775. doi:10.1016/j.acap.2019.11.002 31712182
61 Li R, Fein SB, Grummer-Strawn LM. Association of breastfeeding intensity and bottle-emptying behaviors at early infancy with infants' risk for excess weight at late infancy. Pediatrics. Oct 2008;122 Suppl 2:S77–84. doi:10.1542/peds.2008-1315j 18829835
62 Quah PL, Kleijweg J, Chang YY, Association of sugar-sweetened beverage intake at 18 months and 5 years of age with adiposity outcomes at 6 years of age: the Singapore GUSTO mother-offspring cohort. Article. British Journal of Nutrition. 2019;122(11):1303–1312. doi:10.1017/S0007114519002253 31477198
63 Sonneville KR, Long MW, Rifas-Shiman SL, Kleinman K, Gillman MW, Taveras EM. Juice and water intake in infancy and later beverage intake and adiposity: could juice be a gateway drink? Obesity. Jan 2015;23(1):170–6. doi:10.1002/oby.20927 25328160
64 Wu AJ, Aris IM, Hivert MF, Associations of healthy infant feeding practices and early childhood adiposity in the Rise & SHINE cohort. J Pediatr Gastroenterol Nutr. 2022;75:e15–e19. doi:10.1097/MPG.0000000000003495 35641893
65 Wu AJ, Aris IM, Rifas-Shiman SL, Oken E, Taveras EM, Hivert MF. Longitudinal associations of fruit juice intake in infancy with DXA-measured abdominal adiposity in mid-childhood and early adolescence. Am J Clin Nutr. 2021;114(1):117–123. doi:10.1093/ajcn/nqab043 33829237