# Summary of conclusion statements and grades

The Committee answered the systematic review question, “What is the relationship between complementary feeding and growth, body composition, and risk of obesity?”, with the following conclusion statements. * The grades reflect the strength of the evidence underlying the conclusion statements.

* A conclusion statement is carefully constructed, based on the evidence reviewed, to answer the systematic review question. A conclusion statement does not draw implications and should not be interpreted as dietary guidance.

### Timing of the first introduction of a specific type of complementary food or beverage

- A conclusion statement cannot be drawn about the relationship between the age when infants and young children, up to age 24 months, are introduced to 100% juice and outcomes related to growth patterns, body composition, and risk of obesity during childhood because there is not enough evidence available. (Grade: Grade Not Assignable)
- A conclusion statement cannot be drawn about the relationship between the age when infants and young children, up to age 24 months, are introduced to fruit and outcomes related to growth patterns, body composition, and risk of obesity during childhood because there is not enough evidence available. (Grade: Grade Not Assignable)
- A conclusion statement cannot be drawn about the relationship between the age when infants and young children, up to age 24 months, are introduced to vegetables and outcomes related to growth patterns, body composition, and risk of obesity during childhood because there is not enough evidence available. (Grade: Grade Not Assignable)
- Introducing grains at or before age 4 months is associated with higher BMI z-score during childhood. This conclusion statement is based on evidence graded as limited. (Grade: Limited)
- A conclusion statement cannot be drawn about the relationship between the age when infants and young children, up to age 24 months, are introduced to grains and body composition and risk of obesity during childhood because there is not enough evidence available. (Grade: Grade Not Assignable)
- A conclusion statement cannot be drawn about the relationship between the age when infants and young children, up to age 24 months, are introduced to foods from the protein foods group and outcomes related to growth patterns, body composition, and risk of obesity during childhood because of substantial concerns with consistency in the body of evidence. (Grade: Grade Not Assignable)
- A conclusion statement cannot be drawn about the relationship between the age when infants and young children, up to age 24 months, are introduced to the dairy food group and outcomes related to growth patterns, body composition, and risk of obesity during childhood because there is not enough evidence available, and the evidence that is available has substantial concerns with consistency. (Grade: Grade Not Assignable)
- A conclusion statement cannot be drawn about the relationship between the age when infants and young children, up to age 24 months, are introduced to sugar-sweetened beverages and outcomes related to growth patterns, body composition, and risk of obesity during childhood because of substantial concerns with consistency in the body of evidence. (Grade: Grade Not Assignable)
- A conclusion statement cannot be drawn about the relationship between the age when infants and young children, up to age 24 months, are introduced to food sources of added sugars and outcomes related to growth patterns, body composition, and risk of obesity during childhood because there is not enough evidence available. (Grade: Grade Not Assignable)

### Types and amounts of complementary foods or beverages

- A conclusion statement cannot be drawn about the relationship between 100% juice consumption by infants and young children, up to age 24 months, and outcomes related to growth patterns, body composition, and risk of obesity during childhood because of substantial concerns with consistency and precision in the body of evidence. (Grade: Grade Not Assignable)
- Fruit consumption by infants and young children, up to age 24 months, is not associated with unfavorable outcomes related to growth patterns during childhood. This conclusion statement is based on evidence graded as limited. (Grade: Limited)
- A conclusion statement cannot be drawn about the relationship between fruit consumption by infants and young children, up to age 24 months, and body composition and risk of obesity during childhood because there is not enough evidence available. (Grade: Grade Not Assignable)
- Vegetable consumption by infants and young children, up to age 24 months, is not associated with unfavorable outcomes related to growth patterns during childhood. This conclusion statement is based on evidence graded as limited. (Grade: Limited)
- A conclusion statement cannot be drawn about the relationship between vegetable consumption by infants and young children, up to age 24 months, and body composition and risk of obesity during childhood because there is not enough evidence available. (Grade: Grade Not Assignable)
- Grains consumption by infants and young children, from age 6 months up to age 24 months, is not associated with unfavorable outcomes related to growth patterns and risk of obesity during childhood. This conclusion statement is based on evidence graded as limited. (Grade: Limited)
- A conclusion statement cannot be drawn about the relationship between grains consumption by infants and young children, from age 6 months up to age 24 months, and outcomes related to body composition during childhood because there is not enough evidence available. (Grade: Grade Not Assignable)
- A conclusion statement cannot be drawn about the relationship between consumption of protein foods as a food group by infants and young children, up to age 24 months, and outcomes related to growth patterns, body composition, and risk of obesity during childhood because of substantial concerns with consistency and directness in the body of evidence. (Grade: Grade Not Assignable)
- A conclusion statement cannot be drawn about the relationship between dairy consumption by infants and young children, up to age 24 months, and outcomes related to growth patterns, body composition, and risk of obesity during childhood because of substantial concerns with consistency in the body of evidence. (Grade: Grade Not Assignable)
- Sugar-sweetened beverage consumption by infants, children, and adolescents is associated with unfavorable growth patterns and body composition, and higher risk of obesity in childhood up to early adulthood. This conclusion statement is based on evidence graded as moderate. (Grade: Moderate) *
  * Note: The articles identified in this systematic review were synthesized as part of the systematic review with meta-analysis on sugar-sweetened beverages and growth, body composition, and risk of obesity across the lifespan to avoid duplication of effort ( Deierlein AL, Raynor HA, Byrd-Bredbenner C, . Sugar-Sweetened Beverages and Growth, Body Composition, and Risk of Obesity: A Systematic Review with Meta-Analysis. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review; 2024. 10.52570/NESR.DGAC2025.SR05 ). The relevant conclusion statement from that review is presented here for completeness.
- A conclusion statement cannot be drawn about the relationship between consumption of food sources of added sugars by infants and young children, up to age 24 months, and outcomes related to growth patterns, body composition, and risk of obesity during childhood because there is not enough evidence available. (Grade: Grade Not Assignable)

## Research recommendations

The Committee identified the following research recommendations that describe the research, data, and methodological advances that are needed to strengthen the body of evidence on complementary feeding and growth, body composition, and risk of obesity.

1. Conduct rigorous studies that are designed to assess the impact of complementary foods and beverages on growth, body composition, and risk of obesity.
2. Take a finer developmental lens to the examination of consumption of complementary foods and beverages among infants and young children, particularly from age 6 to 12 months, to better understand how these foods and beverages should be incorporated and contribute to the changing diet.
3. Provide detailed information on the intervention or exposure (i.e., type, amount, frequency, and timing) as well as full daily dietary intake, as applicable.
4. Examine food groups collectively and comprehensively, such that measures reflect a wide range of foods and beverages within each group (e.g., grains, dairy, protein foods), and, in particular, examine measures of protein foods that include both animal sources (e.g., meat, poultry, seafood) and plant sources (e.g., beans, legumes).
5. Measure consumption of 100% juice with greater specificity, such that 100% juice can be assessed separately from beverages such as juice drinks or juice with added sugar.
6. Measure growth, body composition, and risk of obesity at multiple time points, versus single timepoints, to examine change and trajectories in these outcomes relative to differences in complementary feeding
7. Prioritize assessment of outcomes that are most interpretable and useful for assessing growth in infants and young children, such as measures standardized for age and sex.