# Results

## Literature search and screening results

The literature search (Appendix 4) yielded 38,203 search results after the removal of duplicates (see Figure 2). Dual-screening resulted in the exclusion of 35,700 titles, 1,928 abstracts, and 540 full-texts articles. Reasons for full-text exclusion are in Appendix 5. Twenty-three additional articles were identified from the existing reviews ^†^,^‡^ and 7 additional articles were identified from the manual search. The body of evidence included 65 articles:

- Timing of the first introduction of a specific type of complementary food or beverage:
  ▪ 100% juice: 1 article^1^
  ▪ Fruit: 3 articles^2–4^
  ▪ Vegetables: 3 articles^3–5^
  ▪ Grains: 6 articles^3–8^
  ▪ Protein foods: 4 articles^5,8–10^
  ▪ Dairy and fortified soy alternatives: 13 articles^16,8,11–20^
  ▪ SSBs: 9 articles^3,4,6,8,21–25^
  ▪ Food sources of added sugars: 1 article^25^
- Types and amounts of complementary foods and beverages:
  ▪ 100% juice: 4 articles^1,26–28^
  ▪ Fruit: 6 articles^1,6,27,29–3^,^1^
  ▪ Vegetables: 6 articles^1,6,27,29–31^
  ▪ Grains: 14 articles^1,29,30,32–42^
  ▪ Protein foods: 13 articles^1,27,29–31,35,39,41,43–47^
  ▪ Dairy and fortified soy alternatives: 14 articles^14,29,30,45–55^
  ▪ SSBs: 17 articles^1,23,27–30,50,56–65^
  ▪ Food sources of added sugars: 5 articles^1,27,29,30,40^

† English LK, Obbagy JE, Wong YP, . Timing of Introduction of Complementary Foods and Beverages and Growth, Size, and Body Composition: A Systematic Review. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review; 2019. 10.52570/NESR.PB242018.SR0305.

‡ English LK, Obbagy JE, Wong YP, . Types and Amounts of Complementary Foods and Beverages and Growth, Size, and Body Composition: A Systematic Review. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review; 2019. 10.52570/NESR.PB242018.SR0306.

Figure 2 Literature search and screen flowchart

The literature searches in PubMed, Embase, Cochrane, and CINAHL retrieved 38,203 records after removing duplicates. 23 were included from an existing review. 7 were found through other manual search methods. 35,700 titles, 1,928 abstracts, and 540 full-texts were excluded. 65 articles were included in the systematic review.

## Timing of introduction of specific types of complementary foods and beverages

### 100% juice

#### Description of the evidence

One article from a prospective cohort study (PCS) met inclusion criteria and examined the relationship between the timing of introduction of 100% juice in infants and young children, up to age 24 months, and growth, body composition, and risk of obesity (Table 6).^1^ Studies that examined measures of juice introduction that included sugar-sweetened juice or that did not define the juice as being 100% juice were synthesized with the evidence for SSBs.

##### Population

The study was conducted in the United States (specifically, Puerto Rico). The study analytic N was 68 and the article did not report a power calculation related to the timing of introduction to 100% juice and the relevant outcomes.

One hundred percent of the participants in this study were Hispanic. Approximately 68% of mothers had a high school education or higher, and 100% participated in the Special Supplemental Nutrition Program for Women, Infants, and Children (WIC). Approximately 56% of the parents were less than 30 years old. In regards to human milk and formula feeding practices, 51% exclusively breastfed for at least 1 month, approximately 70% were ever formula-fed, and approximately 21% were breastfeeding around 10 months. Forty-seven percent of the children were female. Information on birth size, gestational age, and anthropometry at baseline were not reported.

##### Exposure and comparator

Timing of introduction to 100% juice was assessed through an interviewer-administered questionnaire completed by caregivers when their infants or young children were age 0 to 24 months. Timing of introduction was examined categorically (<6 months versus ≥6 months).

##### Outcome

Trained research staff measured weight and length from age 11 to 36 months in this study. The outcome analyzed by the study was the odds of weight-for-length z-score (WLZ) ≥1, which was calculated based on World Health Organization (WHO) growth charts.

#### Synthesis of the evidence

The single study that met inclusion criteria and assessed timing of introduction to 100% juice reported that introduction before or after age 6 months was not associated with odds of WLZ ≥1 at age 11–36 months (Table 6).^1^

#### Conclusion statement and grade

The Committee did not draw a conclusion statement about the relationship between the timing of introduction of 100% juice in infants and young children, up to age 24 months, and growth, body composition, and risk of obesity because there is not enough evidence available (Table 5). The risk of bias assessments for this body of evidence are documented in Table 7. Publication bias may be a limitation, but the small body of evidence makes it difficult to assess. Additionally, while the literature search was comprehensive, a search of the gray literature was not done, which could increase the possibility of publication bias.

Table 5 Conclusion statement, grade for timing of introduction of 100% juice and growth, body composition, and risk of obesity

Conclusion Statement | A conclusion statement cannot be drawn about the relationship between the age when infants and young children, up to age 24 months, are introduced to 100% juice and outcomes related to growth patterns, body composition, and risk of obesity during childhood because there is not enough evidence available.
Grade | Grade Not Assignable
Body of Evidence | 1 article: 1 prospective cohort study
Rationale | There is not enough evidence available to draw a conclusion statement.

Table 6 Evidence examining the relationship between the timing of introduction to 100% juice and growth, body composition, and risk of obesity ^a^

Study and Participant Characteristics | Exposure, Comparator, and Outcome | Results | Key Confounders, Model Adjustments, and Funding
Amaro-Rivera, 2019 (https://pubmed.ncbi.nlm.nih.gov/31260549/)^1^; PCS, U.S. (Puerto Rico); [underlined: Analytic N] = 68 (Excluded participants lost to follow-up); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race/ethnicity:] Hispanic: 100%; [underlined: Maternal education:] ≤HS: 32.5%, >HS: 67.5%; [underlined: Other SEP measure(s):] WIC participation: 100%; [underlined: Maternal age:] Parent’s age: <30 y: 55.8%, ≥30 y: 44.2%; [underlined: Milk feeding practices:] EBF for ≥1 mo: 51%, Ever FF: 70.1%, Any BF at ~10 mo: 20.8%; [underlined: Child sex (female):] 47%; [underlined: Birth size:] NR; [underlined: Gestational age:] NR | [underlined: Exposure(s) and comparator(s):] Juice (<6 mo vs ≥6 mo); [underlined: Dietary assessment methods:] Interviewer-administered questionnaire completed by caregivers; [underlined: Age(s) at dietary assessment:] 0–24 mo; [underlined: Age of introduction:] <6 mo: 32.5%; [underlined: Outcome(s):] WLZ ≥1; [underlined: Outcome assessment methods:] Weight and length measured by trained research staff. Weight status assessed using WHO age- and sex-specific WLZ growth charts. Relative risk for WLZ (≥1 z-score vs <1 z-score), with underweight defined as WLZ ≤-2 SD, healthy weight status defined as WLZ >-2 and <1 SD, risk of overweight defined as WLZ between 1-<2, and overweight or obesity defined as WLZ ≥2 SD.; [underlined: Age(s) at outcome assessment:] 11–36 mo (Median: 21 mo, 11–23 mo: 61.0%, 24–36 mo: 39.0%) | [underlined: WLZ (≥1 vs <1) @ 11–36 mo] <6 mo vs ≥6 mo: Data NR, NS | [underlined: Key confounders accounted for:] SEP; sex; race and/or ethnicity; milk feeding practices; baseline anthropometry; [underlined: Key confounders NOT accounted for:] gestational age; [underlined: Model adjustments:] WLZ at baseline; [underlined: Funding:] University of Puerto Rico Central Administration Grant; Capacity Advancement in Research Infrastructure; NIMHD

a Abbreviations: @: at; BF: breastfeeding; EBF: exclusive breastfeeding; FF: formula feeding; FFQ: food frequency questionnaire; HS: high school; mo: month; NR: not reported; PCS: prospective cohort study; ref: reference; SD: standard deviation; SEP: socioeconomic position; U.S.: United States; vs: versus; WIC: Special Supplemental Nutrition Program for Women, Infants, and Children; WHO: World Health Organization; WLZ: weight-for-length z-score; y: year

Table 7 Risk of bias for observational studies examining the timing of introduction to 100% juice and growth, body composition, and risk of obesity ^a^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Amaro-Rivera, 2019^1^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH

a Possible ratings of low, some concerns, high, very high, no information, or not applicable determined using the "Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)" tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602. ) *Low risk of bias except for concerns about uncontrolled confounding.

### Fruit

#### Description of the evidence

Three studies met inclusion criteria and examined the relationship between timing of introduction of fruit in infants and young children, up to age 24 months, and growth, body composition, and risk of obesity (Table 9).^2–4^ All studies were PCS, using data from the following cohorts: Generation R,^2^ Project Viva,^4^ and 1 unnamed cohort.^3^

##### Population

The studies were conducted in the United States^3,4^ and the Netherlands.^2^ The analytic sample sizes of the studies were 94, ^3^ 747^2^ and 1,013.^4^ None of the studies reported power calculations related to the timing of introduction of fruit.

Three studies provided information on the racial and/or ethnic background of participants: 100% of participants were White in 1 study,^3^ 100% of participants were of Dutch ethnicity in the second study,^2^ and 69% were White, 12% were Black or African American, 12% were other race and/or ethnicity, 4% were Hispanic and 3% were Asian in the last study.^4^ Across all 3 studies that reported maternal age, the average age of the women was the early thirties.^2–4^ Human milk and formula feeding practices were reported in all 3 studies and varied: 1 study reported that 83% ever breastfed, 33% exclusively breastfed at 4 months, and 12% exclusively breastfed at 6 months^3^; a second study reported that approximately 90% ever breastfed and the mean duration of breastfeeding was about 5 months^2^; the third reported that the rate of any breastfeeding at 4 months was 69%.^4^ Socioeconomic position (SEP), particularly maternal education, was reported in all 3 studies.^2–4^ Two studies reported that at least 50% of participants had a college degree^3,4^ and that the sample in the remaining study had a “higher level of education than the general population”.^2^ Other SEP measures included 1 study reporting that 66% of participants had a household income greater than $70,000 per year,^4^ while the other reported that all participants were from “middle or upper socioeconomic status families”.^3^

Regarding the characteristics of the infants and young children, all 3 studies noted that approximately 50% of participants were female^2–4^ and the mean birth weight was about 3.5 kilograms.^2–4^ Mean gestational age was approximately 40 weeks in 2 studies,^2,4^ and the third study reported that all participants were born full-term.^3^ None of the studies compared baseline growth, body composition, or risk of obesity across exposures.

##### Exposures and comparators

All studies assessed timing of introduction of fruit broadly; none of the studies reported the specific fruits that were included in these measures.^2–4^ The exposure variable was analyzed in various ways across studies. One study analyzed a continuous measure of age of introduction of fruit,^3^ another study compared introduction at less than age 5 months to greater than or equal to age 5 months,^2^ and the third study compared introduction at less than age 4 months or age 6 months or greater to between age 4 months up to age 6 months.^3^ Two studies used a questionnaire to measure timing of introduction of fruit,^2,4^ while the third study used a 24-hour recall.^3^ All of the studies assessed timing of introduction to fruit multiple times between ages 2 and 24 months, all of which included assessments up to age 12 months and 1 that additionally included assessments beyond age 12 months.^3^

##### Outcomes

Each study assessed unique measures of growth and body composition. None of the studies assessed a measure of risk of overweight or obesity. Specifically, the 3 studies analyzed: change in weight, change in length, and change in weight slope relative to length slope from age 2 to 8 months and from age 12 to 24 months,^3^ body mass index (BMI) z-scores (BMIZ) and waist circumference at age 8 and 13 years,^4^ and total sum of skinfolds at age 24 months.^2^ U.S. national reference data was used to BMIZ in the single study that utilized z-scores.^4^ Research staff or nurses measured all outcomes. The age at which the outcome was measured varied from 2 months to 13 years.

#### Synthesis of the evidence

Among the 3 articles that met inclusion criteria, all studies reported null associations between timing of introduction of fruit and growth or body composition (Table 9).^2–4^ The 1 study that reported the direction of the non-significant associations tended to report higher BMIZ and waist circumference with introduction to fruit from 4 to less than 6 months.

#### Conclusion statement and grade

The Committee did not draw a conclusion statement about the relationship between timing of introduction of fruit in infants and young children, up to age 24 months, and growth, body composition, and risk of obesity because there is not enough evidence available (Table 8). The risk of bias assessments for this body of evidence are documented in Table 10. Publication bias may be a limitation, but the small body of evidence makes it difficult to assess. Additionally, while the literature search was comprehensive, a search of the gray literature was not done, which could increase the possibility of publication bias.

Table 8 Conclusion statement, grade for timing of introduction of fruit and growth, body composition, and risk of obesity

Conclusion Statement | A conclusion statement cannot be drawn about the relationship between the age when infants and young children, up to age 24 months, are introduced to fruit and outcomes related to growth patterns, body composition, and risk of obesity during childhood because there is not enough evidence available.
Grade | Grade Not Assignable
Body of Evidence | 3 articles: 3 prospective cohort studies
Rationale | There is not enough evidence available to answer this question.

Table 9 Evidence examining the relationship between timing of introduction to fruit and growth, body composition, and risk of obesity ^a^

Study and Participant Characteristics | Exposure, Comparator, and Outcome | Results | Key Confounders, Model Adjustments, Funding
Ay, 2008 (https://pubmed.ncbi.nlm.nih.gov/18560371/)^2^; PCS, Generation R, Netherlands; [underlined: Analytic N] = 747 (Excluded participants who did not complete skinfold measurements at 24 mo); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race/ethnicity:] Dutch ethnicity (2 parents and 4 grandparents born in the Netherlands): 100%; [underlined: Maternal education:] “higher level of education than the general population”; [underlined: Other SEP measure(s):] NR; [underlined: Maternal age:] ~32 y; [underlined: Milk feeding practices:] Ever BF: ~90%; BF duration: ~5 mo; [underlined: Child sex (female):] 48%; [underlined: Birth weight:] ~3,485 g; [underlined: Gestational age:] 39.8 wk | [underlined: Exposure(s) and comparator(s):] Fruit snack (<5 mo vs ≥5 mo (ref)); [underlined: Dietary assessment methods:] Caregiver questionnaire; [underlined: Age(s) at dietary assessment:] 2, 6, 12 mo; [underlined: Age of introduction:] <5 mo: ~62%, ≥5 mo:~38%; [underlined: Outcome(s):] Sum of skinfold thickness (triceps, biceps, suprailiacal, subscapular); [underlined: Outcome assessment methods:] Skinfold thickness measured by trained medical assistants.; [underlined: Age(s) at outcome assessment:] 24 mo | [underlined: Total sum of skinfolds @ 24 mo] Data NR, p=NS | [underlined: Key confounders accounted for:] SEP; sex; race and/or ethnicity; gestational age; [underlined: Key confounders NOT accounted for:] milk feeding practices; baseline anthropometry; [underlined: Model adjustments:] Age, gender, gestational age, observer, socioeconomic status (maternal age and educational level), smoking during pregnancy; [underlined: Funding:] Erasmus Medical Center; Erasmus University Rotterdam; Netherlands Organization for Health Research and Development; National Diabetic Fund
Carruth, 2000 (https://pubmed.ncbi.nlm.nih.gov/10872903/)^3^; PCS, U.S.; [underlined: Analytic N] = 94 (Reasons for exclusions NR); [underlined: Adequately powered:] Yes; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race/ethnicity:] White: 100%; [underlined: Maternal education:] College degree: 50%; [underlined: Other SEP measure(s):] Hollingshead Index: 54 (9) – all “middle or upper SES families”; [underlined: Maternal age:] 31 y; [underlined: Milk feeding practices:] Ever BF: 83%, EBF at 4 mo: 33%, Mixed feeding at 4 mo: 33%, EBF at 6 mo: 12%; [underlined: Child sex (female):] 46%; [underlined: Birth weight:] Males: 7.8 (1.2) lb, Females: 7.6 (1.1) lb; [underlined: Gestational age:] 100% full-term | [underlined: Exposure(s) and comparator(s):] Fruit (Continuous); [underlined: Dietary assessment methods:] 24-h recall (maternal report) with dietitian; [underlined: Age(s) at dietary assessment:] 2, 3, 4, 6, 8, 10, 12, 16, 20, 24 mo (interviewed 3–5x from 2–10 mo, 2–4x from 12–24 mo); [underlined: Age of introduction:] Median (range): 5.0 (0.5–8.2) mo; [underlined: Outcome(s):] Weight, length, Change in weight slope relative to length slope; [underlined: Outcome assessment methods:] Weight and length measured by research staff; [underlined: Age(s) at outcome assessment:] 2, 3, 4, 6, 8, 10, 12, 16, 20, 24 mo (measured 3–5x from 2–10 mo, 2–4x from 12–24 mo) | [underlined: Change in weight @ 2–8 mo, 12–24 mo (β (SE))]; Change from 2–8 mo: Data NR, p>0.05; Change from 12–24 mo: Data NR, p>0.05; [underlined: Change in length @ 2–8 mo, 12–24 mo (β (SE))]; Change from 2–8 mo: Data NR, p>0.05; Change from 12–24 mo: Data NR, p>0.05; [underlined: Change in weight slope relative to length slope @ 2–8 mo, 12–24 mo (β (SE))]; Change from 2–8 mo: Data NR, p>0.05 Change from 12–24 mo: Data NR, p>0.05 | [underlined: Key confounders accounted for:] SEP; sex; race and/or ethnicity; milk feeding practices; gestational age; baseline anthropometry; [underlined: Key confounders NOT accounted for:] None; [underlined: Model adjustments:] length slope, sex, illness score, breast feeding (duration in mo and ever BF), infant age at first addition of vegetables (for food cluster of meat, mixed, table food), food cluster (meat, mixed food, table food) in the infant’s diet by 8 mo (for vegetables); NA for other analyses (variables not retained in model); [underlined: Funding:] NR
Gingras, 2019 (https://pubmed.ncbi.nlm.nih.gov/31757860/)^4^; PCS, Project Viva, U.S.; [underlined: Analytic N] = 1,013 (Excluded participants who did not have complete exposure data, did not have outcomes measured, and children born <34 wk gestation); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race/ethnicity:] NR (Child race and/or ethnicity: White: 69%, Black or African American: 12%, Other: 12%, Hispanic: 4%, Asian: 3%); [underlined: Maternal education:] College graduate: 74%; [underlined: Other SEP measure(s):] Household income >$70,000/y: 66%; [underlined: Maternal age:] 32.6 (4.8) y; [underlined: Milk feeding practices:] Any BF at 4 mo: 69%; [underlined: Child sex (female):] 51%; [underlined: Birth weight:] 3.53 (0.52) kg; [underlined: Birth weight for gestational age z-score:] 0.23 (0.97); [underlined: Gestational age:] 39.7 (1.4) wk | [underlined: Exposure(s) and comparator(s):] Fruit (<4 mo, 4-<6 mo (ref), ≥6 mo); [underlined: Dietary assessment methods:] Maternal questionnaire; [underlined: Age(s) at dietary assessment:] 6, 12 mo; [underlined: Age of introduction:] <4 mo: 5.7% 4-<6 mo: 60.5%, ≥6 mo: 33.9%; [underlined: Outcome(s):] BMIZ, WC; [underlined: Outcome assessment methods:] All outcomes measured by trained research staff. Age- and sex-specific BMIZ calculated using U.S. national reference data.; [underlined: Age(s) at outcome assessment:] Mean (SD): 7.9 (0.8) y; 13.2 (0.9) y | [underlined: BMIZ @ ~8 y (β (95% CI))]; Among infants BF ≥4 mo:; <4 mo vs 4-<6 mo (ref): 0.22 (−0.17, 0.61); ≥6 mo vs 4-<6 mo (ref): −0.08 (−0.23, 0.06); Among infants FF (never BF or stopped BF by 4 mo):; <4 mo vs 4-<6 mo (ref): 0.11 (−0.24, 0.47); ≥6 mo vs 4-<6 mo (ref): 0.24 (−0.03, 0.50); [underlined: BMIZ @ ~13 y (β (95% CI))]; Among infants BF ≥4 mo:; <4 mo vs 4-<6 mo (ref): 0.27 (−0.15, 0.69); ≥6 mo vs 4-<6 mo (ref): 0.06 (−0.10, 0.22); Among infants FF (never BF or stopped BF by 4 mo):; <4 mo vs 4-<6 mo (ref): 0.11 (−0.30, 0.53); ≥6 mo vs 4-<6 mo (ref): 0.06 (−0.25, 0.36); [underlined: WC (cm) @ ~8 y (β (95% CI))]; Among infants BF ≥4 mo:; <4 mo vs 4-<6 mo (ref): 0.87 (−1.89, 3.64); ≥6 mo vs 4-<6 mo (ref): 0.24 (−0.78, 1.26); Among infants FF (never BF or stopped BF by 4 mo):; <4 mo vs 4-<6 mo (ref): −0.58 (−3.59, 2.42); ≥6 mo vs 4-<6 mo (ref): 0.78 (−1.50, 3.06); [underlined: WC (cm) @ ~13 y (β (95% CI))]; Among infants BF ≥4 mo:; <4 mo vs 4-<6 mo (ref): 3.72 (−0.56, 8.00); ≥6 mo vs 4-<6 mo (ref): 1.03 (−0.57, 2.64); Among infants FF (never BF or stopped BF by 4 mo):; <4 mo vs 4-<6 mo (ref): 0.88 (−4.14, 5.90); ≥6 mo vs 4-<6 mo (ref): −0.50 (−4.21, 3.20) | [underlined: Key confounders accounted for:] SEP; sex; race and/or ethnicity; milk feeding practices; gestational age; baseline anthropometry; [underlined: Key confounders NOT accounted for:] None; [underlined: Model adjustments:] child sex, child age, maternal education level, marital status, household income, maternal prepregnancy BMI, paternal BMI, child’s race and/or ethnicity, gestational age at delivery, change in WAZ from 0 to 4 mo.; [underlined: Funding:] NIH, CIHR

a Abbreviations: @: at; β: beta; BF: breastfeeding; BMI: body mass index; BMIZ: BMI z-score; CI: confidence interval; EBF: exclusive breastfeeding; FF: formula feeding; h: hour; kg: kilogram; lb: pound; mo: month; NA: not applicable; NR: not reported; NS: non-significant; PCS: prospective cohort study; ref: reference; SD: standard deviation; SE: standard error; SEP: socioeconomic position; SES: socioeconomic status; U.S.: United States; WAZ: weight-for-age z-score; WC: waist circumference; wk: week; x: times; y: year

Table 10 Risk of bias for observational studies examining timing of introduction to fruit and growth, body composition, and risk of obesity ^a^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Ay, 2008^2^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | HIGH | HIGH
Carruth, 2000^3^ | LOW | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Gingras, 2019^4^ | LOW | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS

a Possible ratings of low, some concerns, high, very high, no information, or not applicable determined using the "Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)" tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602. ) *Low risk of bias except for concerns about uncontrolled confounding.

### Vegetables

#### Description of the evidence

Three studies met inclusion criteria and examined the relationship between timing of introduction to vegetables in infants and young children, up to age 24 months and growth, body composition, and risk of obesity (Table 12).^3–5^ All studies were PCS, using data from the following cohorts: the Copenhagen Perinatal Cohort,^5^ Project Viva,^4^ and 1 unnamed cohort.^3^

##### Population

The studies were conducted in the Denmark^5^ and the United States.^3,4^ The analytic sample sizes of the studies were 94,^3^ 1,013^4^ and 1,675.^5^ None of the studies reported power calculations related to the timing of introduction of vegetable.

Two studies provided information on the racial and/or ethnic background of participants, reporting that all participants were White in 1 study,^3^ and 69% were White, 12% were Black or African American, 12% were “other” race and/or ethnicity, 4% were Hispanic, and 3% were Asian in the second study.^4^ The average maternal age across studies ranged from the mid-twenties^5^ to early thirties.^3,4^ Human milk and formula feeding practices were reported in all 3 studies and tended to vary: 1 study reported that 83% ever breastfed, 33% exclusively breastfed at 4 months, and 12% exclusively breastfed at 6 months,^3^ a second reported that the median duration of any breastfeeding was 2.5 months,^5^ and the third reported that the rate of any breastfeeding at 4 months was 69%.^4^ SEP was reported in all 3 studies. Maternal education was reported across 2 studies, showing that at least 50% of participants tended to have a college degree.^3,4^3 Additionally, 1 study reported that 66% of participants had a household income greater than $70,000 per year,^4^ another reported that all participants were from “middle or upper socioeconomic status families”,^3^ and the third reported that participants had an average social class score of about 4 on an 8-point scale.^5^ One study recruited participants from a hospital that preferentially admitted mothers with previous or expected pregnancy or delivery complications, or mothers where a home delivery was not advised.^5^

Regarding characteristics of the infants and young children, approximately 50% of participants were female^3,4^ and mean birth weight ranged from approximately 3.2 to 3.5 kilograms.^3–5^ Mean gestational age was approximately 40 weeks in 1 study,^4^ while all participants were born full-term in a second study,^3^ and approximately 18% of infants were born preterm in the third.^5^ None of the studies compared baseline growth, body composition, and risk of obesity across levels of exposures.

##### Exposures and comparators

All studies assessed timing of introduction of vegetables broadly; none of the studies reported the specific vegetables that were included in these measures.^3–5^ The exposure variable was analyzed in various ways across studies. Two studies analyzed age of introduction of vegetables continuously,^3,5^ 1 study examined introduction at age 4 months or later,^5^ and 1 study compared introduction at less than age 4 months or age 6 months or greater to between age 4 months up to age 6 months.^4,5^ One study used a questionnaire to measure timing of introduction of vegetables,^4^ a second conducted a maternal interview,^5^ while the third study used a 24-hour recall.^3^ Two studies assessed timing of introduction to vegetables multiple times^3,4^ while 1 study relied on a single assessment.^5^ The age at which the exposure was measured varied from 2 to 24 months, with all studies including 1 or more assessments through age 1 year and 1 additionally including assessments beyond age 12 months.^3^

##### Outcomes

A variety of growth, body composition, or risk of overweight and obesity measures were assessed across the 3 studies. Specifically, reported outcomes across the 3 studies included: change in weight, change in length, and change in weight slope relative to length slope from age 2–8 months and from age 12–24 months in 1 study;^3^ BMIZ and waist circumference at ages 8 and 13 years in the second study;^4^ and BMIZ reported across multiple time points from age 1 year through age 42 years, in addition to waist circumference, risk of overweight, and risk of obesity at age 42 years, in the third study.^5^ Z-scores were calculated using U.S. national reference data for 1 study,^4^ while a second study utilized growth reference data from Britain (1990) for outcomes measured through adolescence.^5^ Research staff or nurses measured all outcomes, except for weight, height, and waist circumference at 42 years in 1 study.^5^ The age at which the outcome was measured varied from 2 months^3^ to 42 years.^5^

#### Synthesis of the evidence

Among the 3 studies that met inclusion criteria, findings were mixed with all studies reporting null associations, and 2 of these studies also reporting 1 or more significant associations between timing of introduction to vegetables and outcomes related to growth, body composition, or risk of obesity (Table 12).^4,5^ Among the null associations, all 3 studies reported no significant associations between timing of introduction of vegetables and growth, including weight, BMIZ, waist circumference, and risk of obesity. The 1 study that reported the direction of the non-significant associations tended to report higher BMIZ and waist circumference with introduction of vegetables from 4 to less than 6 months.^4^ Two of these studies also reported significant associations, both of which trended towards lower growth or odds of overweight with later introduction of vegetables.^3,5^

#### Conclusion statement and grade

The Committee did not draw a conclusion statement about the relationship between timing of introduction of vegetables in infants and young children, up to age 24 months, and growth, body composition, and risk of obesity because there is not enough evidence available (Table 11). Publication bias may be a limitation, but the small body of evidence makes it difficult to assess. Additionally, while the literature search was comprehensive, a search of the gray literature was not done, which could increase the possibility of publication bias. The risk of bias assessments for this body of evidence are documented in Table 13.

Table 11 Conclusion statement, grade for timing of introduction of vegetables and growth, body composition, and risk of obesity

Conclusion Statement | A conclusion statement cannot be drawn about the relationship between the age when infants and young children, up to age 24 months, are introduced to vegetables and outcomes related to growth patterns, body composition, and risk of obesity during childhood because there is not enough evidence available.
Grade | Grade Not Assignable
Body of Evidence | 3 articles: 3 prospective cohort studies
Rationale | There is not enough evidence available to answer this question.

Table 12 Evidence examining the relationship between timing of introduction to vegetables and growth and body composition ^a^

Study and Participant Characteristics | Exposure, Comparator, and Outcome | Outcome | Key Confounders, Model Adjustments, Funding
Carruth, 2000 (https://pubmed.ncbi.nlm.nih.gov/10872903/)^3^; PCS, U.S.; [underlined: Analytic N] = 94 (Reasons for exclusions NR); [underlined: Adequately powered:] Yes; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race/ethnicity:] White: 100%; [underlined: Maternal education:] College degree: 50%; [underlined: Other SEP measure(s):] Hollingshead Index: 54 (9) – all “middle or upper SES families”; [underlined: Maternal age:] 31 y; [underlined: Milk feeding practices:] Ever BF: 83%, EBF at 4 mo: 33%, Mixed feeding at 4 mo: 33%, EBF at 6 mo: 12%; [underlined: Child sex (female):] 46%; [underlined: Birth weight:] Males: 7.8 (1.2) lb, Females: 7.6 (1.1) lb; [underlined: Gestational age:] 100% full-term | [underlined: Exposure(s) and comparator(s):] Vegetables (Continuous); [underlined: Dietary assessment methods:] 24-h recall (maternal report) with dietitian; [underlined: Age(s) at dietary assessment:] 2, 3, 4, 6, 8, 10, 12, 16, 20, 24 mo (interviewed 3–5x from 2–10 mo, 2–4x from 12–24 mo); [underlined: Age of introduction:] Median (range): 5.5 (1–7.7) mo; [underlined: Outcome(s):] Weight, length, change in weight slope relative to length slope; [underlined: Outcome assessment methods:] Weight and length measured by research staff; [underlined: Age(s) at outcome assessment:] 2, 3, 4, 6, 8, 10, 12, 16, 20, 24 mo (measured 3–5x from 2–10 mo, 2–4x from 12–24 mo) | [underlined: Change in weight @ 2–8 mo, 12–24 mo (β (SE))]; Change from 2–8 mo: Data NR, p>0.05; Change from 12–24 mo: Data NR, p>0.05; [underlined: Change in length @ 2–8 mo, 12–24 mo (β (SE))]; Change from 2–8 mo: Data NR, p>0.05; Change from 12–24 mo: Data NR, p>0.05; [underlined: Change in weight slope relative to length slope @ 2–8 mo, 12–24 mo (β (SE))]; Change from 2–8 mo: −0.0567 (0.0238), p=0.0457; Change from 12–24 mo: Data NR, p>0.05 | [underlined: Key confounders accounted for:] SEP; sex; race and/or ethnicity; milk feeding practices; gestational age; baseline anthropometry; [underlined: Key confounders NOT accounted for:] None; [underlined: Model adjustments:] length slope, sex, illness score, breast feeding (duration in mo and ever BF), infant age at first addition of vegetables (for food cluster of meat, mixed, table food), food cluster (meat, mixed food, table food) in the infant’s diet by 8 mo (for vegetables); NA for other analyses (variables not retained in model); [underlined: Funding:] NR
Gingras, 2019 (https://pubmed.ncbi.nlm.nih.gov/31757860/)^4^; PCS, Project Viva, U.S.; [underlined: Analytic N] = 1,013 (Excluded participants who did not have complete exposure data, did not have outcomes measured, and children born <34 wk gestation); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race/ethnicity:] NR (Child race and/or ethnicity: White: 69%, Black or African American: 12%, Other: 12%, Hispanic: 4%, Asian: 3%); [underlined: Maternal education:] College graduate: 74% Other SEP measure(s): Household income >$70,000/y: 66%; [underlined: Maternal age:] 32.6 (4.8) y; [underlined: Milk feeding practices:] Any BF at 4 mo: 69%; [underlined: Child sex (female):] 51%; [underlined: Birth weight:] 3.53 (0.52) kg; [underlined: Birth weight for gestational age z-score:] 0.23 (0.97); [underlined: Gestational age:] 39.7 (1.4) wk | [underlined: Exposure(s) and comparator(s):] Vegetables (<4 mo, 4-<6 mo (ref), ≥6 mo); [underlined: Dietary assessment methods:] Maternal questionnaire; [underlined: Age(s) at dietary assessment:] 6, 12 mo; [underlined: Age of introduction:] <4 mo: 4.1%, 4-<6 mo: 58.7%, ≥6 mo: 37.2%; [underlined: Outcome(s):] BMIZ, WC; [underlined: Outcome assessment methods:] All outcomes measured by trained research staff. Age- and sex-specific BMIZ calculated using U.S. national reference data.; [underlined: Age(s) at outcome assessment:] Mean (SD): 7.9 (0.8) y; 13.2 (0.9) y | [underlined: BMIZ@ ~8 y (β (95% CI))]; Among infants BF ≥4 mo:; <4 mo vs 4-<6 mo (ref): 0.30 (−0.15, 0.75); ≥6 mo vs 4-<6 mo (ref): −0.08 (−0.22, 0.06); Among infants FF (never BF or stopped BF by 4 mo):; <4 mo vs 4-<6 mo (ref): 0.16 (−0.24, 0.55); ≥6 mo vs 4-<6 mo (ref): 0.18 (−0.07, 0.42); [underlined: BMIZ @ ~13 y (β (95% CI))]; Among infants BF ≥4 mo:; <4 mo vs 4-<6 mo (ref): 0.34 (−0.16, 0.84); ≥6 mo vs 4-<6 mo (ref): 0.08 (−0.08, 0.23); Among infants FF (never BF or stopped BF by 4 mo):; <4 mo vs 4-<6 mo (ref): 0.15 (−0.30, 0.61); ≥6 mo vs 4-<6 mo (ref): 0.01 (−0.26, 0.29); [underlined: WC (cm) @ ~8 y (β (95% CI))]; Among infants BF ≥4 mo:; <4 mo vs 4-<6 mo (ref): 0.75 (−2.45, 3.96); ≥6 mo vs 4-<6 mo (ref): 0.06 (−0.94, 1.06); Among infants FF (never BF or stopped BF by 4 mo):; <4 mo vs 4-<6 mo (ref): −0.20 (−3.53, 3.14); ≥6 mo vs 4-<6 mo (ref): 0.67 (−1.40, 2.74); [underlined: WC (cm) @ ~13 y (β (95% CI))]; Among infants BF ≥4 mo:; <4 mo vs 4-<6 mo (ref): 4.17 (−0.96, 9.30); ≥6 mo vs 4-<6 mo (ref): 0.84 (−0.75, 2.42); Among infants FF (never BF or stopped BF by 4 mo):; <4 mo vs 4-<6 mo (ref): 0.62 (−4.83, 6.07); ≥6 mo vs 4-<6 mo (ref): −0.93 (−4.27, 2.41) | [underlined: Key confounders accounted for:] SEP; sex; race and/or ethnicity; milk feeding practices; gestational age; baseline anthropometry; [underlined: Key confounders NOT accounted for:] None; [underlined: Model adjustments:] child sex, child age, maternal education level, marital status, household income, maternal prepregnancy BMI, paternal BMI, child’s race and/or ethnicity, gestational age at delivery, change in WAZ from 0 to 4 mo.; [underlined: Funding:] NIH, CIHR
Schack-Nielsen, 2010 (https://pubmed.ncbi.nlm.nih.gov/20032492/)^5^; PCS, Copenhagen Perinatal Cohort, Denmark; [underlined: Analytic N] = 5,068 (N for individual analyses ranged from 367–1,675) (Excluded participants without information on BF, introduction of spoon feeding, birth weight, and/or at least 1 BMI measurement from 1–42 y.); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race/ethnicity:] NR; [underlined: Maternal education:] NR; [underlined: Other SEP measure(s):] Social class: ~4.0 (1–8 point scale; 8=highest); Breadwinner’s education: ~2.4 (1–4 point scale; 4=highest); [underlined: Maternal age:] ~26 y; [underlined: Milk feeding practices:] Duration of any BF (median (10th, 90th percentile)): 2.50 (0.23, 6.50) mo; [underlined: Child sex (female):] NR; [underlined: Birth weight:] 3,232 (588) g; [underlined: Gestational age:] ~18% preterm (≤37 wk); [underlined: Other relevant characteristics:] Participants were recruited from a hospital that preferentially admitted mothers with previous or expected pregnancy/delivery complications and mothers where a home delivery was not advised (primarily single mothers). | [underlined: Exposure(s) and comparator(s):]; Vegetables (Continuous (mo); ≥4 mo vs <4 mo (ref)); [underlined: Dietary assessment methods:] Maternal interview; [underlined: Age(s) at dietary assessment:] 1 y; [underlined: Age of introduction:] 4.05 (1.34) mo; [underlined: Outcome(s):] BMIZ, overweight, obesity, WC; [underlined: Outcome assessment methods:] Weight and height at 1, 3, and 6 y measured by study personnel. Weight and height from 7–14 y measured at school health examinations. Weight and height for men from 16–23 y measured at draft board examinations. Weight and height at 20–34 y measured by study personnel. Weight, height, and WC at 42 y was self-reported. Childhood BMIZ calculated using British 1990 growth references adjusted for sex and age. Internal, sex-specific BMIZ were created for adults (20–34 y and 42 y).; [underlined: Age(s) at outcome assessment:] 1, 3, 6, 7, 8, 9, 10, 11, 12, 13, 14, 16–23 (draft board; men), 20–34, 42 y | [underlined: BMIZ @ 1, 3, 6, 7, 8, 9, 10, 11, 12, 13, 14, 16–23 (draft board; men only), 20–34, 42 y (β (95% CI))] Continuous; 1, 3, 6, 7, 8, 9, 10, 11, 12, 13, 14, 16–23 y (draft board; men only): All data NR, p=NS; 20–34 y: −0.072 (−0.133, −0.010); 42 y: −0.064 (−0.101, −0.027); [underlined: WC (cm) @ 42 y (β (95% CI))]; Continuous Data NR, p=NS; [underlined: Overweight @ 42 y (OR (95% CI)]; Continuous: 0.90 (0.81, 0.98); Categorical: Lower risk with later introduction (data NR), p=0.046; [underlined: Obesity @ 42 y (OR (95% CI)]; Continuous: 0.89 (0.76, 1.03); Categorical: Data NR | [underlined: Key confounders accounted for:] SEP; sex; milk feeding practices; gestational age; [underlined: Key confounders NOT accounted for:] race and/or ethnicity; baseline anthropometry; [underlined: Model adjustments:] Duration of BF, sex, maternal age at birth, prepregnancy BMI, gestational weight gain, smoking during pregnancy, social class, breadwinner’s education, single mother status, prematurity, BMI (analysis of waist circumference only); [underlined: Funding:] NICHD; NIDA; The Danish Research Council; Danish National Board of Health; The National Danish Science Foundation; The National Danish Agricultural and Veterinary Research Council

a Abbreviations: @: at; β: beta; BF: breastfeeding; BMI: body mass index; BMIZ: BMI z-score; CI: confidence interval; EBF: exclusive breastfeeding; FF: formula feeding; h: hour; kg: kilogram;; lb: pound; mo: month; NA: not applicable; NR: not reported; NS: non-significant; OR: odds ratio; PCS: prospective cohort study; ref: reference; SD: standard deviation; SDS: standard deviation score; SE: standard error; SEP: socioeconomic position; SES: socioeconomic status; U.S.: United States; WAZ: weight-for-age z-score; WC: waist circumference; wk: week; x: times; y: year

Table 13 Risk of bias for observational studies examining timing of introduction to vegetables and growth, body composition, and risk of obesity ^a^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Carruth, 2000^3^ | LOW | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Gingras, 2019^4^ | LOW | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Schack-Nielsen, 2010^5^ (Outcome at 1–34 y) | SOME CONCERNS | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Schack-Nielsen, 2010^5^ (Outcome at 42 y) | SOME CONCERNS | SOME CONCERNS | LOW | LOW | HIGH | SOME CONCERNS | SOME CONCERNS | HIGH

a Possible ratings of low, some concerns, high, very high, no information, or not applicable determined using the "Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)" tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602. ) *Low risk of bias except for concerns about uncontrolled confounding.

### Grains

#### Description of the evidence

Six studies met inclusion criteria and examined the relationship between the timing of introduction of grains in infants and young children, up to age 24 months, and growth, body composition, and risk of obesity (Table 15).^3–8^ All 6 studies were PCS, using data from the following cohorts: the Copenhagen Perinatal Cohort,^5^ Global Exploration of Human Milk (GEHM),^8^ Project Viva,^4^ TARget Kids!,^7^ the WIC Infant and Toddler Feeding Practices Study-2 (ITFPS-2),^6^ and 1 unnamed study.^3^

##### Population

The studies were conducted in the United States,^3,4,6,8^ Canada,^7^ China,^8^ Denmark,^5^ and Mexico.8 The analytic sample sizes of the studies ranged from 94^3^ to 8,943,^7^ although the sample sizes for most analyses were less than 2,000.^3–6,8^ None of the studies reported power calculations related to the timing of introduction to grains and the relevant outcomes.

Four studies provided information on the racial and/or ethnic background of participants. Three studies predominantly or exclusively included participants who were White or European,^3,4,7^ but in 2 of these studies individuals of other races and/or ethnicities were represented including individuals who identified as African, African American or Black, Asian, Hispanic, and Latin American.^4,7^ The fourth study had a more racially and ethnically diverse group of participants, with ~41% of participants being Hispanic and ~25% of participants being non-Hispanic Black.^6^ Maternal age, reported in 5 studies, typically ranged, on average, from the mid-twenties to the early thirties.^3–6,8^ Human milk and formula feeding practices were reported in all studies, showing that breastfeeding was initiated in a large proportion of the participants, while duration and exclusivity of breastfeeding varied.^3–8^ SEP was reported in all 6 studies using a variety of metrics. Maternal education was reported in 4 studies: a large proportion of participants attended or graduated from college in 3 studies,^3,4,8^ while 1 study included a larger proportion of participants who had a high school level of education or less.^6^ Household income was reported in 3 studies: 1 which reported that 66% participants had a household income >$70,000 per year,^4^ 1 which reported that 64% of participants were at or below 75% of the U.S. poverty guideline,^6^ and 1 which reported that 32% and 42% of participants had a family income of 80,000–149,999 CAD and ≥150,000 CAD, respectively.^7^ WIC participation was reported in 2 studies: in 1 study all individuals were participating in WIC^6^ and in the other, among participants from the United States, approximately 34% participated in WIC.^8^

The children enrolled in these studies were approximately 50% female. The mean birth weight ranged from approximately 3.2 kilograms^5^ to 3.5 kilograms.^3,4^ Regarding gestational age, 5 studies reported that most or all participants were born term,^5–8^ while the sixth study reported that the mean gestational age at birth was 39.7 weeks.^4^ Baseline anthropometry was not reported in most studies.^3–6,8^

##### Exposures and comparators

The studies examined the timing of introduction to a small number of grains products including cereal or infant cereal,^3,4,6,7^ “firm food” (i.e., “soaked bread and biscuits),^5^ and cereals more broadly (e.g., bread, tortillas, rice, cereal, pasta).^8^ Timing of introduction to these products was examined continuously in 4 studies^3,5,6,8^ and categorically in 3 studies.^4,5,7^ However, 1 study that modeled timing of introduction continuously did so on the basis of adherence to guidelines, such that introduction both before and after age 6 to 7 months (age of maximum score) received lower scores.^6^ Among the studies that examined timing of introduction categorically, 1 compared ≥4 months to <4 months,^5^ 1 compared 4 months, 5 months, and 6 months,7 and 1 compared 4 to <6 months to <4 months and ≥6 months.^4^ The dietary assessment methods included 24-hour recall,^3,6^ 24-hour food frequency recall,^8^ and questionnaires or interviews, ^4,5,7^ completed by a mother or caregiver. For 3 studies, frequent assessments throughout infancy were conducted.^3,6,8^

##### Outcomes

Growth, body composition, and risk of obesity were assessed using a variety of measures. Outcomes related to growth were reported in all 6 studies,^3–8^ with the most common outcome being BMIZ. One study examined measures of body composition4 and 2 studies examined odds of overweight and obesity.^5,7^ These outcomes were almost all measured by study personnel, with the exception of a single assessment in 1 study.^5^ Z-scores were calculated using growth standards from the WHO,^7,8^ the Centers for Disease Control and Prevention (CDC),^4,6^ and Britain (1990).^5^ The outcomes were assessed at a wide range of ages: 4 studies assessed outcomes among infants and young children up to age 24 months,^3,5,7,8^ 4 studies assessed outcomes among children,^4–7^ and 1 study assessed outcomes among adolescents and adults.^5^

#### Synthesis of the evidence

Among the 6 articles that met inclusion criteria and analyzed outcomes related to growth, 3 studies reported a mix of statistically significant and nonsignificant findings,^4,5,7^ while 3 studies reported exclusively null findings^3,6,8^ (Table 15) The 3 studies that reported statistically significant findings all examined BMIZ, and the direction and magnitude of these results were consistent. The first study found that introduction to infant cereal at age 4 months compared to age 6 months was associated with slightly higher BMIZ at age 1 and 10 years, while associations with BMIZ at age 5 and comparisons with introduction at age 5 months were statistically nonsignificant, but trended in the same direction.^7^ Height-for-age z-score (HAZ) was also examined in this study, and while introduction to infant cereals at age 4 or 5 months was associated with higher HAZ at age 1 year compared to introduction at age 6 months, statistically significant differences in HAZ were no longer present at either age 5 or 10 years.^7^ A second study reported that introduction to infant cereal <4 months, compared to introduction at 4 to <6 months, was associated with slightly higher BMIZ at age 8 years, as well as at age 13 years (but only among individuals who breastfed for less than 4 months; the association among individuals who were breastfed for at least 4 months was statistically non-significant but trended in the same direction).^4^ Finally, the third study examined timing of introduction to “firm food” (i.e., soaked bread and biscuits) continuously and found that later introduction was associated with slightly lower BMIZ at ages 1, 10, and 11 years, but reported no significant association with BMIZ at any other age at assessment from childhood through adulthood.^5^ All 3 of these studies analyzed several hundreds or thousands of participants,^4,5,7^ including 1 study which analyzed approximately 8,900 participants.^7^ The remaining 3 studies did not detect any statistically significant associations between timing of introduction to grains and outcomes related to growth, including BMIZ, weight-for-age z-score (WAZ), weight, length-for-age z-score (LAZ), and length; none of the studies reported the directionality of any non-significant trends.^3,6,8^ While all 3 studies examined timing of introduction to grains, 1 study modeled age of introduction based on degree of adherence to guidelines (i.e., lower scores for introduction to iron-rich cereal both before and after age 6–7 months) versus directly by increasing age, limiting the comparability of these results to those of the other studies.^6^ In sum, among studies that examined BMIZ, there was consistency of results such that the direction of both statistically significant and non-significant associations tended to be similar (among the 3 studies that reported this information). Further, among those studies that detected associations between timing of introduction of grains and BMIZ, 2 examined a similar cut-point (approximately age 4 months) and the sample sizes were relatively large ranging from approximately 350 participants to 8,900 participants. Other growth outcomes were less frequently reported across studies.

Few studies examined body composition or the odds of overweight and/or obesity as an outcome (Table 15).^4,5,7^ Although a similar pattern of results was observed, with all reporting a mix of null associations and statistically significant associations between earlier introduction and greater waist circumference or odds of overweight and/or obesity, the small number of studies on these topics limit the ability to draw conclusions.

#### Conclusion statements and grades

The Committee developed a conclusion statement about the relationship between the timing of introduction of grains and growth, specifically BMIZ, based on their review of the body of evidence (Table 14). The grade reflects the strength of the evidence underlying the conclusion statement. However, the Committee did not draw a conclusion statement about the relationship between the timing of introduction of grains and body composition and risk of obesity because there is not enough available evidence (Table 14). The risk of bias assessments for this body of evidence are documented in Table 16.

Table 14 Conclusion statements, grades for timing of introduction to grains and growth and timing of introduction to grains and body composition and risk of obesity

Conclusion Statement | Introducing grains at or before age 4 months is associated with higher BMI z-score during childhood. This conclusion is based on evidence graded as limited.
Grade | Limited
Body of Evidence | 6 articles (6 studies): 6 prospective cohort studies
Consistency | Some concerns with consistency due to some inconsistency in the significance of findings.
Precision | Some concerns with precision due to few studies and small effect sizes.
Risk of bias | Some concerns with risk of bias, particularly due to confounding and exposure measurement.
Directness | Minimal concerns with directness
Generalizability | Some concerns with generalizability due to more limited applicability to the U.S. population.
Conclusion Statement | A conclusion statement cannot be drawn about the relationship between the age when infants and young children, up to age 24 months, are introduced to grains and body composition and risk of obesity during childhood because there is not enough evidence available.
Grade | Grade Not Assignable
Body of Evidence | 3 articles: 3 prospective cohort studies
Rationale | There is not enough evidence available to draw a conclusion statement.

##### Assessment of the evidence

The body of evidence underlying the graded conclusion statement above includes 6 articles from 6 PCS. The evidence was graded based on an assessment of 5 grading elements, as described below. Publication bias was also a consideration; however, this was not assessed as a serious concern because the body of evidence included studies that reported only nonsignificant findings as well as studies that reported a mix of both significant and nonsignificant results, across a range of analytic sample sizes. However, while the literature search was comprehensive, a search of the gray literature was not done, which could increase the possibility of publication bias.

###### Consistency

There was some inconsistency in the results; specifically, half of the studies reported a mix of statistically significant and non-significant results while half reported exclusively null results. However, the direction of the statistically significant results were consistent, with earlier introduction to grains, particularly before 4 months of age, associated with greater BMIZ, including both studies that assessed age of introduction to grains categorically. Further, the non-significant associations reported in these studies predominantly trended in the same direction. There was some inconsistency among the studies regarding the type of grains product under study, with 4 studies examining cereal or infant cereal, 1 study examining “firm food” (i.e., soaked bread and biscuits), and 1 study examining cereal products more broadly.

###### Precision

Only 6 studies examined the relationship between timing of introduction to grains and outcomes related to growth, 5 of which examined BMIZ. The analytic sample sizes ranged from 94 to 8,943, although most studies had an analytic sample size between 350 and 2,000 participants. The effect sizes, when reported, were generally small. None of the studies provided information regarding statistical power.

###### Risk of bias

There were several risk of bias concerns across the body of evidence (Table 16). Four studies did not account for all key confounders, 4 studies had some concerns regarding the methods of exposure measurement, and a pre-registered analysis plan was not available for any of the studies. Additionally, risk of bias due to missing data was of concern for half of the studies. Risk of bias due to selection of participants, post-exposure interventions, and outcome measurement were assessed as low for most or all studies.

###### Directness

There was some inconsistency in the results; specifically, half of the studies reported a mix of statistically significant and non-significant results while half reported exclusively null results. However, the direction of the statistically significant results were consistent, with earlier introduction to grains, particularly before 4 months of age, associated with greater BMIZ, including both studies that assessed age of introduction to grains categorically. Further, the non-significant associations reported in these studies predominantly trended in the same direction. There was some inconsistency among the studies regarding the type of grains product under study, with 4 studies examining cereal or infant cereal, 1 study examining “firm food” (i.e., soaked bread and biscuits), and 1 study examining cereal products more broadly.

###### Precision

Only 6 studies examined the relationship between timing of introduction to grains and outcomes related to growth, 5 of which examined BMIZ. The analytic sample sizes ranged from 94 to 8,943, although most studies had an analytic sample size between 350 and 2,000 participants. The effect sizes, when reported, were generally small. None of the studies provided information regarding statistical power.

###### Risk of bias

There were several risk of bias concerns across the body of evidence (Table 16). Four studies did not account for all key confounders, 4 studies had some concerns regarding the methods of exposure measurement, and a pre-registered analysis plan was not available for any of the studies. Additionally, risk of bias due to missing data was of concern for half of the studies. Risk of bias due to selection of participants, post-exposure interventions, and outcome measurement were assessed as low for most or all studies.

###### Directness

The populations, exposures, comparators, and outcomes examined in the studies are directly related to the systematic review question. Specifically, all 6 studies examined timing of introduction to grains and outcomes related to growth. However, most studies examined timing of introduction to a single grain product (e.g., infant cereal) rather than assessing introduction to grains more broadly as a food group.

###### Generalizability

Four studies were conducted in the United States, either in part or in full, while the remaining studies were conducted in Canada, Denmark, China, and Mexico. Most of the studies tended to include participants with higher average levels of education and income, and who were predominantly White or European, with more limited representation of individuals from other racial and/or ethnic groups. However, some studies did include or focus on individuals with relatively lower SEP or were more racially and/or ethnically diverse.

Table 15 Evidence examining the relationship between timing of introduction to grains and growth, body composition, and risk of obesity ^a^

Study and Participant Characteristics | Exposure, Comparator, and Outcome | Results | Key Confounders, Model Adjustments, and Funding
Au, 2023 (https://pubmed.ncbi.nlm.nih.gov/36806452/)^6^; PCS, WIC ITFPS-2, U.S.; [underlined: Analytic N] = 1,523 (24 mo), 1,680 (36 mo), 1,872 (48 mo) (Excluded participants with missing data on HEI-2015 or BMI at 2, 3, or 4 y, born prematurely, had very low birth weight, or had long-term medical problems that could affect eating.); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race and/or ethnicity:] Hispanic: 40.6%, Non-Hispanic White: 29.1%, Non-Hispanic African American: 24.8%, Non-Hispanic Other: 5.5%; Maternal education: <HS: 24.4%, HS: 37.7%, >HS: 37.5%; [underlined: Other SEP measure(s):] Participating in WIC: 100%; Maternal employment at 6 mo: Full-time: 21.5%, Part-time: 20.2%, Not working for pay: 58.2%; Poverty level at enrollment: ≤75% of poverty guideline: 64.0%, >75-<130%: 26.3%, >130% poverty: 9.7%; [underlined: Maternal age:] 16–19 y: 11.7%, 20–25 y: 41.1%, ≥26 y: 47.3%; [underlined: Milk feeding practices:] Any BF: 81.9%; Any formula use: 95.5%; [underlined: Child sex (female):] 49%; [underlined: Birth weight:] Low (<2.5 kg): 5.3%, Normal (2.5-≤4.5 kg): 93.4%, High (>4.5 kg): 1.3%; [underlined: Gestational age:] Excluded infants born prematurely | [underlined: Exposure(s) and comparator(s):] Iron-rich cereals (Continuous; Infant Diet Quality Index component score from 0–1 based on degree of adherence to guidelines; max score: introduced at 6–7 mo); [underlined: Dietary assessment methods:] 24-h dietary recall via telephone interview with caregiver; [underlined: Age(s) at dietary assessment:] 1, 3, 5, 7, 9 11, 13, 15, 18, 24, 30, 36, 42, and 48 mo; [underlined: Age of introduction:] 6–7 mo: 36.2%; [underlined: Outcome(s):] BMIZ; [underlined: Outcome assessment methods:] Weight and length/height collected at WIC sites or from child’s health care provider. BMIZ based on CDC age- and sex-specific growth charts; [underlined: Age(s) at outcome assessment:] 2, 3, 4 y | [underlined: BMIZ @ 2, 3, 4 y]; 2 y: Data NR, p>0.10; 3 y: Data NR, p>0.10; 4 y: Data NR, p>0.10 | [underlined: Key confounders accounted for:] SEP; sex; gestational age; [underlined: Key confounders NOT accounted for:] race and/or ethnicity; milk feeding practices; baseline anthropometry; [underlined: Model adjustments:] None; [underlined: Funding:] NHLBI; USDA/NIFA
Carruth, 2000 (https://pubmed.ncbi.nlm.nih.gov/36806452/)^3^; PCS, U.S.; [underlined: Analytic N] = 94 (Reasons for attrition NR); [underlined: Adequately powered:] Yes; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race and/or ethnicity]: White: 100%; [underlined: Maternal education:] College degree: 50%; [underlined: Other SEP measure(s):] Hollingshead Index: 54 (9) – all “middle or upper SES families”; [underlined: Maternal age:] 31 y; [underlined: Milk feeding practices]: Ever BF: 83%, EBF at 4 mo: 33%, Mixed feeding at 4 mo: 33%, EBF at 6 mo: 12%; [underlined: Child sex (female)]: 46%; [underlined: Birth weight:] Males: 7.8 (1.2) lb, Females: 7.6 (1.1) lb; [underlined: Gestational age:] 100% full-term | [underlined: Exposure(s) and comparator(s):] Cereal (Continuous); [underlined: Dietary assessment methods:] 24-h recall (maternal report) with dietitian; [underlined: Age(s) at dietary assessment]: 2, 3, 4, 6, 8, 10, 12, 16, 20, 24 mo (interviewed 3–5x from 2–10 mo, 2–4x from 12–24 mo); [underlined: Age of introduction:] Median (range): 4.0 (0.5–6.5) mo; [underlined: Outcome(s):] Weight, length, Change in weight slope relative to length slope; [underlined: Outcome assessment methods:] Weight and length measured by research staff; [underlined: Age(s) at outcome assessment:] 2, 3, 4, 6, 8, 10, 12, 16, 20, 24 mo (measured 3–5x from 2–10 mo, 2–4x from 12–24 mo) | [underlined: Change in weight @ 2–8 mo, 12–24 mo (β (SE))]; Change from 2–8 mo: Data NR, p>0.05; Change from 12–24 mo: Data NR, p>0.05; [underlined: Change in length @ 2–8 mo, 12–24 mo (β (SE))]; Change from 2–8 mo: Data NR, p>0.05; Change from 12–24 mo: Data NR, p>0.05; [underlined: Change in weight slope relative to length slope @ 2–8 mo, 12–24 mo (β (SE))]; Change from 2–8 mo: Data NR, p>0.05; Change from 12–24 mo: Data NR, p>0.05 | [underlined: Key confounders accounted for:] SEP; sex; race and/or ethnicity; milk feeding practices; gestational age; baseline anthropometry; [underlined: Key confounders NOT accounted for:] None; [underlined: Model adjustments:] NA (cereal not retained in model); [underlined: Funding:] NR
D’Hollander, 2022 (https://pubmed.ncbi.nlm.nih.gov/34481809/)^7^; PCS, TARGet Kids!, Canada; [underlined: Analytic N] = 8,943 (Excluded children who were never introduced to infant cereal (too young at survey) or were introduced to a different solid food first.); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race and/or ethnicity:] European: 62.8%, Asian: 19.6%, Other (mixed, Arab): 8.7%, African: 5.7%, Latin American: 3.2%; [underlined: Maternal education:] NR; [underlined: Other SEP measure(s):] Family income (Canadian $): ≤29,999: 7.7%; 30,000–79,999: 18.3%; 80,000–149,999: 32.2%; ≥150,000: 41.8%; [underlined: Maternal age:] NR; [underlined: Milk feeding practices:] During first y – Predominantly BF: 59.9%; Predominantly formula fed: 17.2%; Mixed: 22.9%; [underlined: Child sex (female):] 48%; [underlined: Birth weight:] 3.3 (0.6) kg; [underlined: Gestational age:] ≥37 wk: 89.2% | [underlined: Exposure(s) and comparator(s):] Infant cereal (4 mo, 5 mo, 6 mo); [underlined: Dietary assessment methods:] Caregiver report via nutrition questionnaire adapted from Canadian Community Health Survey; [underlined: Age(s) at dietary assessment:] Surveyed 2x/y until age 2 y, annually until age 10 y; first response after introduction of infant cereal used (mean = 2.2 y); [underlined: Age of introduction:] 4 mo: 18.8%, 5 mo: 21.6%, 6 mo: 44.7%; [underlined: Outcome(s):] BMIZ, zHeight, underweight, overweight, obesity; [underlined: Outcome assessment methods:] Height and weight measured by trained research assistants. BMIZ and zHeight scores and categories determined using WHO growth standards and cut-offs; underweight, BMIZ < −2; normal weight, −2 ≤ BMIZ ≤ 1, overweight, 1 < BMIZ ≤2; obesity, BMIZ > 2.; [underlined: Age(s) at outcome assessment:] Measured 2x/y until age 2 y, annually until age 10 y | [underlined: BMIZ @ 1 y, 5 y, 10 y (β (95% CI))]; Infant cereal at 4 mo vs 6 mo (ref); 1 y: 0.06 (0.01, 0.12), p=0.03; 5 y: 0.03 (−0.03, 0.08), p=0.39; 10 y: 0.17 (0.06, 0.28), p=0.002; Infant cereal at 5 mo vs 6 mo (ref); 1 y: Data NR, p=NS; 5 y: Data NR, p=NS 10 y: Data NR, p=NS; Infant cereal at 4 mo vs 5 mo (ref); 1 y: Data NR, p=NS; 5 y: Data NR, p=NS; 10 y: Data NR, p=unclear; [underlined: zHeight @ 1 y, 5 y, 10 y (β (95% CI))]; Infant cereal at 4 mo vs 6 mo (ref); 1 y: 0.09 (0.04, 0.15), p=0.002; 5 y: −0.02 (−0.08, 0.04), p=0.53; 10 y: 0.03 (−0.08, 0.14), p=0.63; Infant cereal at 5 mo vs 6 mo (ref); 1 y: 5mo > 6mo (Data NR), p<0.05; 5 y: Data NR, p=NS 10 y: Data NR, p=NS; Infant cereal at 4 mo vs 5 mo (ref); 1 y: Data NR, p=NS; 5 y: Data NR, p=NS 10 y: Data NR, p=NS; [underlined: Underweight @ 1 y, 5 y, 10 y (OR (95% CI))]; Infant cereal at 4 mo vs 6 mo (ref) 1 y: 1.08 (0.85, 1.38), p=0.54; 5 y: 0.72 (0.43, 1.22), p=0.22; 10 y: 0.32 (0.08, 1.23), p=0.10; [underlined: Overweight @ 1 y, 5 y, 10 y (OR (95% CI))]; Infant cereal at 4 mo vs 6 mo (ref); 1 y: 1.03 (0.87, 1.22), p=0.70; 5 y: 1.05 (0.89, 1.24), p=0.55; 10 y: 1.12 (0.80, 1.62), p=0.54; [underlined: Obesity @ 1 y, 5y, 10 y (OR (95% CI))]; Infant cereal at 4 mo vs 6 mo (ref); 1 y: 1.25 (0.93, 1.69), p=0.14; 5 y: 1.28 (0.96, 1.71), p=0.10; 10 y: 1.82 (1.18, 2.80), p=0.006 | [underlined: Key confounders accounted for:] SEP; sex; race and/or ethnicity; milk feeding practices; gestational age; [underlined: Key confounders NOT accounted for:] baseline anthropometry; [underlined: Model adjustments:] Predominant feeding type in first year of life (breast milk, formula, or mixed), birth weight, child sex, gestational age, parental ethnicity, family income, sugar-sweetened beverage intake, cow’s milk volume, bottle feeding and nonlinear time introduced to infant cereal (restricted cubic splines, 5 knots), child age (restricted cubic splines, 5 knots; effect modifier; zHeight and weight status only), maternal BMI (BMIZ and weight status only), maternal height (zHeight only); [underlined: Funding:] Canadian Institutes of Health Research (CIHR) Institute of Human Development, Child and Youth Health
Gingras, 2019 (https://pubmed.ncbi.nlm.nih.gov/31757860/)^4^; PCS, Project Viva, U.S.; [underlined: Analytic N] = 1,013 (Excluded participants who did not have complete exposure data, did not have outcomes measured, and children born <34 wk gestation); [underlined: Adequately powered:] NR; Participant Characteristics (Mean (SD) unless otherwise noted); [underlined: Race and/or ethnicity:] NR (Child race and/or ethnicity: White: 69%, Black or African American: 12%, Other: 12%, Hispanic: 4%, Asian: 3%); [underlined: Maternal education:] College graduate: 74% Other SEP measure(s): Household income >$70,000/y: 66%; [underlined: Maternal age:] 32.6 (4.8) y; [underlined: Milk feeding practices:] Any BF at 4 mo: 69%; [underlined: Child sex (female):] 51%; [underlined: Birth weight:] 3.53 (0.52) kg; [underlined: Birth weight for gestational age z score:] 0.23 (0.97); [underlined: Gestational age:] 39.7 (1.4) wk | [underlined: Exposure(s) and comparator(s):] Infant cereal (<4 mo, 4-<6 mo (ref), ≥6 mo); [underlined: Dietary assessment methods:] Maternal questionnaire; [underlined: Age(s) at dietary assessment:] 6, 12 mo; [underlined: Age of introduction:] <4 mo: 15.3%, 4-<6 mo: 69.4%, ≥6 mo 15.3%; [underlined: Outcome(s):] BMIZ, WC; [underlined: Outcome assessment methods:] All outcomes measured by trained research staff. Age- and sex-specific BMIZ calculated using U.S. national reference data.; [underlined: Age(s) at outcome assessment:] Mean (SD): 7.9 (0.8) y; 13.2 (0.9) y | [underlined: BMIZ @ ~8 y (β (95% CI))]; Among infants BF ≥4 mo:; <4 mo vs 4-<6 mo (ref): 0.28 (0.03, 0.53); ≥6 mo vs 4-<6 mo (ref): −0.08 (−0.26, 0.11); Among infants FF (never BF or stopped BF by 4 mo):; <4 mo vs 4-<6 mo (ref): 0.33 (0.09, 0.57); ≥6 mo vs 4-<6 mo (ref): 0.35 (−0.02, 0.73); [underlined: BMIZ @ ~13 y (β (95% CI))]; Among infants BF ≥4 mo:; <4 mo vs 4-<6 mo (ref): 0.20 (−0.08, 0.47); ≥6 mo vs 4-<6 mo (ref): −0.04 (−0.24, 0.16); Among infants FF (never BF or stopped BF by 4 mo):; <4 mo vs 4-<6 mo (ref): 0.31 (0.02, 0.59); ≥6 mo vs 4-<6 mo (ref): 0.17 (−0.27, 0.60); [underlined: WC (cm) @ ~8 y (β (95% CI))]; Among infants BF ≥4 mo:; <4 mo vs 4-<6 mo (ref): 2.24 (0.46, 4.01); ≥6 mo vs 4-<6 mo (ref): 0.12 (−1.18, 1.42); Among infants FF (never BF or stopped BF by 4 mo):; <4 mo vs 4-<6 mo (ref): 2.58 (0.49, 4.66); ≥6 mo vs 4-<6 mo (ref): 2.33 (−0.82, 5.48); [underlined: WC (cm) @ ~13 y (β (95% CI))]; Among infants BF ≥4 mo:; <4 mo vs 4-<6 mo (ref): 3.02 (0.21, 5.82); ≥6 mo vs 4-<6 mo (ref): 0.67 (−1.35, 2.68); Among infants FF (never BF or stopped BF by 4 mo):; <4 mo vs 4-<6 mo (ref): 3.10 (−0.39, 6.58); ≥6 mo vs 4-<6 mo (ref): 1.77 (−3.38, 6.92) | [underlined: Key confounders accounted for:] SEP; sex; race and/or ethnicity; milk feeding practices; gestational age; baseline anthropometry; [underlined: Key confounders NOT accounted for:] None; [underlined: Model adjustments:] child sex, child age, maternal education level, marital status, household income, maternal prepregnancy BMI, paternal BMI, child’s race and/or ethnicity, gestational age at delivery, change in WAZ score from 0 to 4 mo.; [underlined: Funding]: NIH, CIHR
Schack-Nielsen, 2010 (https://pubmed.ncbi.nlm.nih.gov/20032492/)^5^; PCS, Copenhagen Perinatal Cohort, Denmark; [underlined: Analytic N] = 5,068 (N for individual analyses ranged from 367–1,675) (Excluded participants without information on BF, introduction of spoon feeding, birth weight, and/or at least 1 BMI measurement from 1–42 y.); [underlined: Adequately powered:] NR; Participant Characteristics (Mean (SD) unless otherwise noted); [underlined: Race and/or ethnicity]: NR; [underlined: Maternal education:] NR; [underlined: Other SEP measure(s)]: Social class: ~4.0 (1–8 point scale; 8=highest); Breadwinner’s education: ~2.4 (1–4 point scale; 4=highest); [underlined: Maternal age:] ~26 y; [underlined: Milk feeding practices:] Duration of any BF (median (10th, 90th percentile)): 2.50 (0.23, 6.50) mo; [underlined: Child sex (female):] NR; [underlined: Birth weight:] 3,232 (588) g; [underlined: Gestational age:] ~18% preterm (≤37 wk); [underlined: Other relevant characteristics:] Participants were recruited from a hospital that preferentially admitted mothers with previous or expected pregnancy/delivery complications and mothers where a home delivery was not advised (primarily single mothers). | [underlined: Exposure(s) and comparator(s):] Firm food (also described as “soaked bread and biscuits”) (Continuous (mo); ≥4 mo vs <4 mo (ref)); [underlined: Dietary assessment methods:] Maternal interview; [underlined: Age(s) at dietary assessment:] 1 y; [underlined: Age of introduction:] 8.10 (2.08) mo; [underlined: Outcome(s):] BMIZ, overweight, obesity; [underlined: Outcome assessment methods:] Weight and height at 1, 3, and 6 y measured by study personnel.; Weight and height from 7–14 y measured at school health examinations.; Weight and height for men from 16–23 y measured at draft board examinations.; Weight and height at 20–34 y measured by study personnel.; Weight and height at 42 y was self-reported.; Childhood BMIZ calculated using British 1990 growth references adjusted for sex and age. Internal, sex-specific BMIZ were created for adults (20–34 y and 42 y).; [underlined: Age(s) at outcome assessment:] 1, 3, 6, 7, 8, 9, 10, 11, 12, 13, 14, 16–23 (draft board; men), 20–34, 42 y | [underlined: BMIZ @ 1, 3, 6, 7, 8, 9, 10, 11, 12, 13, 14, 16–23 (draft board; men only), 20–34, 42 y (β (95% CI))]; Age at introduction to firm food (continuous) 3, 6, 7, 8, 9, 12, 13, 14, 16–23 (draft board; men only), 20–34 y: All data NR, p=NS; 1 y: −0.053 (−0.082, −0.024); 10 y: −0.054 (−0.096, −0.012); 11 y: −0.057 (−0.101, −0.013); 42 y: −0.022 (−0.048, 0.004); [underlined: Overweight @ 42 y (OR (95% CI)]; Age at introduction to firm food; Continuous: 0.92 (0.86, 0.98); Categorical: Data NR, p=NS; [underlined: Obesity @ 42 y (OR (95% CI)]; Age at introduction to firm food; Continuous: 1.00 (0.90, 1.11); Categorical: Data NR, p=NR | [underlined: Key confounders accounted for:] SEP; sex; milk feeding practices; gestational age; [underlined: Key confounders NOT accounted for:] race and/or ethnicity; baseline anthropometry; [underlined: Model adjustments:] Duration of BF, sex, maternal age at birth, prepregnancy BMI, gestational weight gain, smoking during pregnancy, social class, breadwinner’s education, single mother status, prematurity, birth weight, weight at 1 y (analysis of BMIZ for timing of any only), BMI (analysis of WC only); [underlined: Funding:] NICHD; NIDA; The Danish Research Council; Danish National Board of Health; The National Danish Science Foundation; The National Danish Agricultural and Veterinary Research Council
Woo, 2013 (https://pubmed.ncbi.nlm.nih.gov/23236024/)^8^; PCS, GEHM, China, Mexico, U.S.; [underlined: Analytic N] = 285 (Excluded participants who were lost to follow-up); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race and/or ethnicity]: NR (Country: China: ~36%, Mexico: ~31%, U.S.: ~32%); [underlined: Maternal education]: China, Mexico, U.S., respectively: ≤HS graduate: 18.3%, 93.2%, 5.0%, Attended or graduated from college: 72.5%, 5.9%, 78.3%, Post-college education: 9.2%, 0.8%, 16.7%; [underlined: Other SEP measure(s):] Employed at time of pregnancy: 71.4% (China), 40.7% (Mexico), 80.8% (U.S.); WIC (U.S.): ~34%, Nutrisano supplemental food program (Mexico): 0%, Supplemental food programs in Shanghai (China): 0%; [underlined: Maternal age:] 29.3 (3.7) y (China), 24.4 (5.6) y (Mexico), 31.5 (5.2) y (U.S.); [underlined: Milk feeding practices:] EBF duration (median (IQR)): China: 4.9 (1.6, 11.9) wk, Mexico: 7.1 (0.0, 18.0) wk, U.S.: 13.7 (4.6, 19.3) wk. BF duration (median): China: 37.1 wk, Mexico: 52.0 wk, U.S.: 49.5 wk; [underlined: Child sex (female):] 49%; [underlined: Birth weight]: ~3.4 kg; [underlined: Gestational age:] 100% ≥37 wk gestation | [underlined: Exposure(s) and comparator(s):] Cereals (e.g., bread, tortillas, rice, cereal, pasta) (Continuous; mo); [underlined: Dietary assessment methods:] Maternal 24 h food frequency recall via telephone.; [underlined: Age(s) at dietary assessment:] 2–52 wk, weekly; [underlined: Age of introduction:] Median (IQR) for China, Mexico, and U.S., respectively (mo): Bread or cereal: 4.3 (4.1, 4.6), 6.7 (6.2, 7.6), 5.4 (4.4, 6.1); [underlined: Outcome(s):] WAZ, LAZ, BMIZ; [underlined: Outcome assessment methods:] Weight and length measured by trained study personnel. WAZ, LAZ, and BMIZ calculated using age- and sex-specific z-scores from the 2005 WHO infant growth standards.; [underlined: Age(s) at outcome assessment:] 1 y | [underlined: WAZ @ 1 y]; Data NR, p≥0.20; [underlined: LAZ @ 1 y]; Data NR, p≥0.20; [underlined: BMIZ @ 1 y]; Data NR, p≥0.20 | [underlined: Key confounders accounted for:] SEP; sex; milk feeding practices; gestational age; [underlined: Key confounders NOT accounted for:] race and/or ethnicity; baseline anthropometry; [underlined: Model adjustments:] Cohort site; [underlined: Funding:] Mead Johnson Nutrition Inc; NIH/NICHD; NIH/NCRR (Institutional Clinical and Translational Science Award)

a Abbreviations: @: at; β: beta; BF: breast feeding; BMI: body mass index; BMIZ: BMI z-score; CI: confidence interval; cm: centimeter; d: day; DXA: Dual-energy X-ray absorptiometry; EBF: exclusive breast feeding; FF: formula fed; g: gram; GEHM: Global Exploration of Human Milk; h: hour; HS: high school; IQR: interquartile range; kg: kilogram; LAZ: length-for-age z-score; mm: millimeter; mo: month; NR: not reported; NS: non-significant; OR: odds ratio; PCS: prospective cohort study; ref: reference; SD: standard deviation; SE: standard error; SEP: socioeconomic position; SES: Socioeconomic status; TARGet Kids: The Applied research Group for Kids!; U.S.: United States; WAZ: weight-for-age z-score; WC: waist circumference; WHO: World Health Organization; WIC: Special Supplemental Nutrition Program for Women, Infants, and Children; WC: waist circumference; wk: week; y: year

Table 16 Risk of bias for observational studies examining timing of introduction to grains and growth, body composition, and risk of obesity ^a^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Au, 2023^6^ | HIGH | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Carruth, 2000^3^ | LOW | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
D’Hollander, 2022^7^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Gingras, 2019^4^ | LOW | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Schack-Nielsen, 2010^5^ (all time points except 42 y) | SOME CONCERNS | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Schack-Nielsen, 2010^5^ (42 y time point) | SOME CONCERNS | SOME CONCERNS | LOW | LOW | HIGH | SOME CONCERNS | SOME CONCERNS | HIGH
Woo, 2013^8^ | VERY HIGH | SOME CONCERNS | LOW | LOW | LOW | LOW | HIGH | VERY HIGH

a Possible ratings of low, some concerns, high, very high, no information, or not applicable determined using the "Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)" tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602. ) *Low risk of bias except for concerns about uncontrolled confounding.

### Protein foods

#### Description of the evidence

Four studies met inclusion criteria and examined the relationship between timing of introduction of foods from the protein foods group among infants and young children, up to age 24 months, and growth, body composition, and risk of obesity (Table 18).^5,8–10^ All 4 studies were PCS, using data from the following cohorts: the Copenhagen Perinatal Cohort,^5^ GEHM,^8^ Infant Feeding Practices Study II (IFPS II),^10^ and Project Viva.^9^

##### Population

Two studies were conducted in the United States,^9,10^ 1 study was conducted in Denmark,^5^ and 1 study included participants from China, Mexico, and the United States.^8^ The analytic sample sizes ranged from 285^8^ to 1,675.^5^ No studies reported whether the samples were sufficiently powered to detect differences in growth, body composition, and risk of overweight or obesity outcomes by age of introduction of protein foods.

Among the 2 studies that provided information on the racial and/or ethnic background of participants, both studies reported that greater than 70% of participants were non-Hispanic White.^9,10^ Average maternal age ranged from mid-twenties to early-thirties.^5,8–10^ Human milk and formula feeding practices were reported in 2 studies: the first study reported a median duration of any breastfeeding of 2.5 months,^5^ and the second study reported a median duration of any and exclusive breastfeeding that ranged from 37.1 to 52.0 weeks and 4.9 weeks to 13.7 weeks, respectively, with the longest median durations in the United States and the shortest median durations in China.^8^ Maternal education was reported across 3 studies,^8–10^ 1 which reported that 44.8% had a college degree or higher,^10^ 1 which reported that 75.9% had a college degree or higher,^9^ and a third which reported that 72.5%, 5.9%, and 78.3% attended or graduated from college in China, Mexico, and the United States, respectively.^8^ Other measures of SEP were provided in all 4 studies. One study reported that 68% of participants had a household income greater than $70,000 per year,^9^ 1 study reported that 61% of participants had family incomes above 185% of the federal poverty level (FPL),10 a third reported that about 34% of the sample participated in WIC,^8^ and the fourth study reported that participants had an average social class score of about 4 on an 8-point scale.^5^ This final study also recruited participants from a hospital that preferentially admitted mothers with previous or expected pregnancy or delivery complications and mothers where a home delivery was not advised.^5^

Regarding the characteristics of the infants and young children, approximately 50% of participants were female^8–10^ and the mean birth weight ranged from 3.2 to 3.5 kilograms.^5,8–10^ Regarding gestational age, 1 study enrolled only term infants,^8^ 1 study reported that most infants (95.7%) were born term,^10^ another study reported that approximately 18% of infants were born preterm, and the last study reported that the mean gestational age was 39.5 weeks.^9^ No studies reported baseline growth, body composition, or risk of obesity.

##### Exposures and comparators

Of the studies that assessed timing of introduction of foods from the protein foods group, 3 examined eggs,^5,9,10^ 1 examined meat,^5^ and 1 examined high protein foods (e.g., egg, meat, fish, and legumes).^8^ The exposure variable was analyzed continuously in 3 studies^5,8,10^ and categorically in 2 studies, examining cut points at 4 months^5^ and 12 months.^9^ To measure timing of introduction of foods from the protein foods group, 2 studies used a questionnaire,^9,10^ 1 study conducted maternal interviews,^5^ and 1 study collected 24-hour food frequency recalls.^8^ Half of the studies assessed timing of introduction of foods from the protein foods group multiple times up to age 1 year,^8,10^ and the other half measured the exposure at age 1 year only.^5,9^ The age at which the exposure was measured varied from 2 weeks^8^ to 1 year.^5,8–10^

##### Outcomes

All 4 studies assessed growth,^5,8–10^ 1 study assessed body composition,^9^ and 3 studies assessed risk of overweight or obesity.^5,9,10^ BMIZ was the most common outcome measure, having been assessed in all 4 studies. Other growth parameters included WAZ,^8^ LAZ,^8^ weight-for-height z-score (WHZ),^10^ HAZ,^10^ wasting,^10^ and stunting.^10^ Measures of body composition included total fat mass, trunk fat mass and lean mass.^9^ Z-scores were calculated based on WHO,^8–10^ CDC,^10^ or British growth standards.^5^ The age at which the outcomes were examined ranged widely from age 12 months to age 42 years, although most studies assessed the outcomes prior to adulthood. Research staff or nurses measured all outcomes, except for 1 timepoint (age 42 years) in 1 study which relied on self-report of weight, height, and waist circumference.^5^

#### Synthesis of the evidence

Among the 4 studies that met inclusion criteria,^5,8–10^ findings were mixed with all 4 studies reporting null associations between the timing of introduction of protein foods and growth, body composition, and risk of obesity, 3 of which also reported significant associations between the age of introduction of protein foods and outcomes related to growth and body composition (Table 18). Among the null associations, all 4 studies reported non-significant associations between timing of introduction of eggs^5,9,10^ and high-protein foods^8^ and growth outcomes, most commonly BMIZ, across ages 1 to 42 years, body composition at various timepoints,^9^ and risk of obesity.^5,9,10^ The effect sizes were small and the directionality of results was mixed. Among the significant associations, eggs (1 study^10^) and meat (1 study^5^ tended to be significantly associated with lower growth^5,10^ and body composition^9^ outcomes.

The ability to draw conclusions from this body of evidence were limited by inconsistency of the exposures and how they were categorized. Specifically, the foods examined varied including eggs, meat, and high-protein foods more broadly. Additionally, the exposure variables were analyzed in multiple ways, either continuously up to age 12 months or categorically at ages 4 or 12 months.

#### Conclusion statement and grade

The Committee did not draw a conclusion statement about the relationship between timing of introduction of foods from the protein foods group in infants and young children, up to age 24 months, and growth, body composition, and risk of obesity because of substantial concerns with consistency (Table 17). The foods examined as part of timing of introduction of the protein foods group varied from eggs, meat, to high-protein foods, including eggs, meat, fish, and legumes. Additionally, the exposure variable was analyzed in various ways, either measured continuously up to 12 months, or categorically at 12 months. Publication bias may be a limitation, but the small body of evidence makes it difficult to assess. However, while the literature search was comprehensive, a search of the gray literature was not done, which could increase the possibility of publication bias. The risk of bias assessments for this body of evidence are documented in Table 19.

Table 17 Conclusion statement, grade for foods from the protein foods group consumption and growth, body composition, and risk of obesity

Conclusion Statement | A conclusion statement cannot be drawn about the relationship between the age when infants and young children, up to age 24 months, are introduced to foods from the protein foods group and outcomes related to growth patterns, body composition, and risk of obesity during childhood because of substantial concerns with consistency in the body of evidence.
Grade | Grade Not Assignable
Body of Evidence | 4 articles: 4 prospective cohort studies
Rationale | The studies were not consistent in the exposures measured and there was variability in how timing was categorized.

Table 18 Evidence examining the relationship between the timing of introduction to protein foods and growth, body composition, and risk of obesity ^a^

Study and Participant Characteristics | Exposure, Comparator, and Outcome | Results | Key Confounders, Model Adjustments, Funding
Choudhary, 2023 (https://pubmed.ncbi.nlm.nih.gov/36913449/)^9^; PCS, Project Viva, U.S.; [underlined: Analytic N] = 1,089 (Excluded participants with missing data on infant age at egg introduction and BMIZ at all time points.); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race and/or ethnicity:] Non-Hispanic White: 76.8%, non-Hispanic Black: 9.2%, Hispanic: 5.6%, Asian: 5.0%, >1 race or other: 3.4%; [underlined: Maternal education:] No college degree: 24.1%, College degree or above: 75.9%; [underlined: Other SEP measure(s):] Household annual income: ≤$70,000: 32.3%, >$70,000: 67.7%; [underlined: Maternal age:] 32.7 (4.5) y; [underlined: Milk feeding practices:] NR; [underlined: Child sex (female):] 51%; [underlined: Birth weight:] 3,502 (561) g; [underlined: Gestational age:] 39.5 (1.8) wk | [underlined: Exposure(s) and comparator(s):] Egg (≤12 mo vs >12 mo (ref)); [underlined: Dietary assessment methods:] Maternal questionnaire; [underlined: Age(s) at dietary assessment:] 1 y; [underlined: Age of introduction:] ≤12 mo: 88.7%, >12 mo: 11.3%; [underlined: Outcome(s):] Risk of obesity, BMIZ, fat mass, trunk fat mass, lean mass; [underlined: Outcome assessment methods:] Weight and height measured by trained research assistants. Age- and sex-specific BMIZ and percentiles were based on WHO Child Growth Standards. Child obesity defined as sex- and age-specific BMI ≥95th percentile. Fat mass and lean mass measured using DXA.; [underlined: Age(s) at outcome assessment:] 3 y, 7–10 y, 12–13 y | [underlined: BMIZ @ 3, 7–10, 12–13 y (mean difference (95% CI))]; ≤12 mo vs >12 mo (ref); 3 y: 0.04 (−0.14, 0.23), p=0.651; 7–10 y: 0.12 (−0.11, 0.35), p=0.320; 12–13 y: −0.04 (−0.29, 0.21), p=0.756; Across all: 0.01 (−0.16, 0.17), p=0.948; [underlined: Females:]; 3 y: 0.01 (−0.23, 0.25), p=0.962; 7–10 y: 0.00 (−0.30, 0.29), p=0.974; 12–13 y: −0.27 (−0.60, 0.06), p=0.112; Across all: −0.09 (−0.30, 0.13), p=0.423; [underlined: Males:]; 3 y: 0.09 (−0.20, 0.37), p=0.548; 7–10 y: 0.28 (−0.08, 0.64), p=0.132; 12–13 y: 0.20 (−0.16, 0.57), p=0.272; Across all: 0.13 (−0.12, 0.38), p=0.304; [underlined: Total fat mass @ 7–10, 12–13 y (mean difference (95% CI))]; ≤12 mo vs >12 mo (ref); 7–10 y: −0.05 (−0.46, 0.36), p=0.801; 12–13 y: −0.34 (−1.03, 0.36), p=0.343; Across both: −0.20 (−0.69, 0.28), p=0.411; [underlined: Females:]; 7–10 y: −0.41 (−0.96, 0.15), p=0.152; 12–13 y: −1.23 (−2.14, −0.31), p=0.009; Across both: −0.75 (−1.44, −0.07), p=0.032; [underlined: Males:]; 7–10 y: 0.44 (−0.15, 1.03), p=0.146; 12–13 y: 0.68 (−0.36, 1.71), p=0.199; Across both: 0.49 (−0.12, 1.11), p=0.115; [underlined: Trunk fat mass @ 7–10, 12–13 (mean difference (95% CI))]; ≤12 mo vs >12 mo (ref); 7–10 y: 0.03 (−0.15, 0.22), p=0.716; 12–13 y: −0.18 (−0.52, 0.16), p=0.293; Across both: −0.07 (−0.30, 0.15), p=0.523; [underlined: Females:]; 7–10 y: −0.10 (−0.35, 0.16), p=0.460; 12–13 y: −0.57 (−1.01, −0.12), p=0.013; Across both: −0.30 (−0.61, 0.01), p=0.058; [underlined: Males:]; 7–10 y: 0.22 (−0.04, 0.48), p=0.102; 12–13 y: 0.29 (−0.21, 0.78), p=0.254; Across both: 0.22 (−0.09, 0.52), p=0.162; [underlined: Lean mass @ 7–10, 12–13 (mean difference (95% CI))]; ≤12 mo vs >12 mo (ref); 7–10 y: 0.05 (−0.25, 0.35), p=0.731; 12–13 y: −0.17 (−0.62, 0.28), p=0.453; Across both: −0.04 (−0.36, 0.28), p=0.795; [underlined: Females:]; 7–10 y: 0.07 (−0.33, 0.48), p=0.716; 12–13 y: −0.44 (−1.04, 0.16), p=0.153; Across both: −0.07 (−0.48, 0.33), p=0.721; [underlined: Males:]; 7–10 y: 0.07 (−0.38, 0.53), p=0.749; 12–13 y: 0.27 (−0.40, 0.94), p=0.427; Across both: 0.06 (−0.44, 0.55), p=0.814; [underlined: Risk of obesity @ 3, 7–10, 12–13 y (OR (95% CI))]; ≤12 mo vs >12 mo (ref); 3 y: 1.05 (0.59, 1.86), p=0.864; 7–10 y: 1.23 (0.63, 2.44), p=0.543; 12–13 y: 1.33 (0.67, 2.63), p=0.417; Across all: 1.11 (0.70, 1.78), p=0.657; [underlined: Females:]; 3 y: 0.67 (0.31, 1.48), p=0.328; 7–10 y: 0.84 (0.35, 1.97), p=0.681; 12–13 y: 0.64 (0.26, 1.55), p=0.319; Across all: 0.68 (0.38, 1.24), p=0.210; [underlined: Males:]; 3 y: 1.56 (0.67, 3.62), p=0.304; 7–10 y: 2.39 (0.70, 8.12), p=0.163; 12–13 y: 3.23 (0.95, 11.00), p=0.061; Across all: 1.97 (0.90, 4.30), p=0.090 | [underlined: Key confounders accounted for:] SEP; sex; race and/or ethnicity; gestational age; [underlined: Key confounders NOT accounted for:] milk feeding practices; baseline anthropometry; [underlined: Model adjustments:] Obesity and BMIZ: Maternal age, prepregnancy BMI, household annual income; Total, trunk, and lean mass: Maternal age, prepregnancy BMI, household annual income, child age at outcome assessment, child sex; [underlined: Funding:] Egg Nutrition Center/American Egg Board; NIH
Mi, 2022 (https://pubmed.ncbi.nlm.nih.gov/35712809/)^10^; PCS, IFPS II, U.S.; [underlined: Analytic N] = 993 (Excluded participants with missing data on exposure and outcomes, or with extreme z-score values.); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race and/or ethnicity:] Non-Hispanic White: 86.5%, Hispanic: 5.5%, Asian/Pacific Islander and others: 4.2%, Non-Hispanic Black: 3.8%; [underlined: Maternal education:] 3 y college or lower: 55.2%, College graduate or higher: 44.8%; [underlined: Other SEP measure(s):] Family income (% of the US federal poverty level): >185%: 61.3% ≤185%: 38.7%; [underlined: Maternal age:] 18–24 y: 17.3%, 25–29 y: 34.5%, 30–34 y: 30.0%, ≥35 y: 18.3%; [underlined: Milk feeding practices:] NR; [underlined: Child sex (female):] 51%; [underlined: Birth weight:] 3,442.9 (472.0) g; [underlined: Birth length:] 50.9 (2.6) cm; [underlined: Gestational age:] 95.7% full term (≥37 wk) | [underlined: Exposure(s) and comparator(s):] Eggs (Continuous (mo)); [underlined: Dietary assessment methods:] Maternal questionnaire of infant food intake in past 7 d; [underlined: Age(s) at dietary assessment:] 2, 3, 4, 5, 6, 7, 9, 10, 12 mo; [underlined: Age of introduction:] 2 mo: 0.12%, 3 mo: 0.23%, 4 mo: 0.29%, 5 mo: 0.47%, 6 mo: 1.86%, 7 mo: 5.42%, 9 mo: 12.59%, 10 mo: 18.53%, 12 mo: 36.01%, >12 mo: 24.48%; [underlined: Outcome(s):] BMIZ, WHZ, HAZ, Obesity, Wasting, Stunting; [underlined: Outcome assessment methods:] Weight, height at their most recent doctor’s visit reported by mother. Z-scores calculated using WHO growth charts (0–2 y) and CDC growth charts (≥2 y).; Obesity defined as WHZ ≥3 at 12 mo or BMIZ ≥2 at 6 y, wasting defined as WHZ < −2 at 12 mo and 6 y, and stunting defined as HAZ < −2 at 12 mo and 6 y.; [underlined: Age(s) at outcome assessment:] 12 mo, 6 y | [underlined: BMIZ @ 12 mo, 6 y (Mean difference (95% CI))]; 12 mo: −0.01 (−0.06, 0.04), p=0.664; 6 y: 0.00 (−0.04, 0.04), p=0.952; [underlined: Females:]; 12 mo: −0.06 (−0.13, 0.00), p=0.060; 6 y: 0.00 (−0.05, 0.06), p=0.952; [underlined: Males:]; 12 mo: 0.04 (−0.03, 0.11), p=0.281; 6 y: 0.00 (−0.06, 0.06), p=0.975; [underlined: Sex x Timing of introduction interaction:]; 12 mo: p=0.036; 6 y: p=0.874; [underlined: WHZ @ 12 mo, 6 y (Mean difference (95% CI))]; 12 mo: −0.01 (−0.05, 0.04), p=0.761; 6 y: 0.02 (−0.03, 0.06), p=0.396; [underlined: Females:]; 12 mo: −0.06 (−0.12, 0.00), p=0.045; 6 y: 0.01 (−0.04, 0.07), p=0.658; [underlined: Males:]; 12 mo: 0.05 (−0.02, 0.11), p=0.176; 6 y: 0.03 (−0.04, 0.09), p=0.763; [underlined: Sex x Timing of introduction interaction:]; 12 mo: p=0.018; 6 y: p=0.763; [underlined: HAZ @ 12 mo, 6 y (Mean difference (95% CI))]; 12 mo: 0.01 (−0.05, 0.07), p=0.738; 6 y: −0.08 (−0.12, −0.03), p<0.001; [underlined: Females:]; 12 mo: 0.07 (−0.03, 0.16), p=0.182; 6 y: −0.08 (−0.14, −0.02), p=0.006; [underlined: Males:]; 12 mo: −0.05 (−0.12, 0.03), p=0.198; 6 y: −0.07 (−0.13, −0.01), p=0.017; [underlined: Sex x Timing of introduction interaction:] 12 mo: p=0.069; 6 y: p=0.827; [underlined: Wasting (RR (95% CI))]; 12 mo: 0.84 (0.68, 1.04), p=0.105; 6 y: 0.96 (0.82, 1.11), p=0.562; [underlined: Females:]; 12 mo: 0.86 (0.58, 1.13), p=0.302; 6 y: 0.95 (0.74, 1.16), p=0.655; [underlined: Males:]; 12 mo: 0.82 (0.55, 1.10), p=0.208; 6 y: 0.96 (0.76, 1.16), p=0.698; [underlined: Sex x Timing of introduction interaction:] 12 mo: p=0.819; 6 y: p=0.997; [underlined: Stunting (RR (95% CI))]; 12 mo: 0.95 (0.86, 1.05), p=0.331; 6 y: 1.17 (1.03, 1.33), p=0.016; [underlined: Females:]; 12 mo: 0.91 (0.78, 1.03), p=0.147; 6 y: 1.16 (0.99, 1.33), p=0.063; [underlined: Males:]; 12 mo: 1.02 (0.86, 1.17), p=0.821; 6 y: 1.18 (0.99, 1.37), p=0.064; [underlined: Sex x Timing of introduction interaction:] 12 mo: p=0.526; 6 y: p=0.988; [underlined: Obesity @ 12 mo, 6 y (RR (95% CI))]; 12 mo: 0.99 (0.84, 1.16), p=0.868; 6 y: 0.96 (0.88, 1.05), p=0.388; [underlined: Females:]; 12 mo: 0.83 (0.64, 1.01), p=0.067; 6 y: 0.98 (0.85, 1.11), p=0.783; [underlined: Males:]; 12 mo: 1.24 (0.95, 1.54), p=0.108; 6 y: 0.94 (0.83, 1.06), p=0.336; [underlined: Sex x Timing of introduction interaction:]; 12 mo: p=0.015; 6 y: p=0.64 | [underlined: Key confounders accounted for:] SEP; sex; race and/or ethnicity; milk feeding practices; gestational age; [underlined: Key confounders NOT accounted for:] baseline anthropometry; [underlined: Model adjustments:] Maternal sociodemographic characteristics (e.g., age, education level, family income, race/ethnicity, and marital status), health behaviours/status during pregnancy (e.g., preconception BMI, gestational weight gain, and gestational duration), child sex, corresponding growth measurement at birth, infant age at introducing other complementary foods; [underlined: Funding:] Egg Nutrition Centre/American Egg Board; Health Resources and Services Administration of HHS; Chinese National Key Research and Development Programme of China; National Natural Science Foundation of China; Natural Science Basic Research Plan of the Shaanxi Province; Fundamental Research Funds for the Central Universities; Xi’an Special Science and Technology Projects
Schack-Nielsen, 2010 (https://pubmed.ncbi.nlm.nih.gov/20032492/)^5^; PCS, Copenhagen Perinatal Cohort, Denmark; [underlined: Analytic N] = 5,068 (N for individual analyses ranged from 367–1,675; Excluded participants without information on BF, introduction of spoon feeding, birth weight, and/or at least 1 BMI measurement from 1–42 y.); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race and/or ethnicity:] NR; [underlined: Maternal education:] NR; [underlined: Other SEP measure(s):] Social class: ~4.0 (1–8 point scale; 8=highest); Breadwinner’s education: ~2.4 (1–4 point scale; 4=highest); [underlined: Maternal age:] ~26 y; [underlined: Milk feeding practices:] Duration of any BF (median (10th, 90th percentile)): 2.50 (0.23, 6.50) mo; [underlined: Child sex (female):] NR; [underlined: Birth weight:] 3,232 (588) g; [underlined: Gestational age:] ~18% preterm (≤37 wk); [underlined: Other relevant characteristics:] Participants were recruited from a hospital that preferentially admitted mothers with previous or expected pregnancy/delivery complications and mothers where a home delivery was not advised (primarily single mothers). | [underlined: Exposure(s) and comparator(s):] Eggs, Meat (continuous (mo); ≥4 mo vs <4 mo (ref)); [underlined: Dietary assessment methods:] Maternal interview; [underlined: Age(s) at dietary assessment:] 1 y; [underlined: Age of introduction:] Eggs: 6.08 (1.84) mo; Meat: 6.87 (1.92) mo; [underlined: Outcome(s):] BMIZ, overweight, obesity, WC; [underlined: Outcome assessment methods:] Weight and height at 1, 3, and 6 y measured by study personnel. Weight and height from 7–14 y measured at school health examinations. Weight and height for men from 16–23 y measured at draft board examinations. Weight and height at 20–34 y measured by study personnel. Weight, height, and WC at 42 y was self-reported.; Childhood BMIZ calculated using British 1990 growth references adjusted for sex and age. Internal, sex-specific BMIZ were created for adults (20–34 y and 42 y).; [underlined: Age(s) at outcome assessment:] 1, 3, 6, 7, 8, 9, 10, 11, 12, 13, 14, 16–23 (draft board; men), 20–34, 42 y | [underlined: BMIZ @ 1, 3, 6, 7, 8, 9, 10, 11, 12, 13, 14, 16–23 (draft board; men only), 20–34, 42y (β (95% CI))]; Age at introduction to eggs (continuous) 1, 3, 6, 7, 8, 9, 10, 11, 12, 13, 14, 16–23 (draft board; men only), 20–34, 42 y: All data NR, p=NS; Age at introduction to meat (continuous) 1, 3, 6, 7, 8, 9, 10, 11, 12, 13, 14, 16–23 (draft board; men only), 20–34 y: All data NR, p=NS; 42 y: −0.032 (−0.059, −0.005); [underlined: Overweight @ 42 y (OR (95% CI)]; Age at introduction to eggs; Continuous: 0.98 (0.91, 1.05); Categorical: Data NR, p=NS; Age at introduction to meat; Continuous: 0.93 (0.87, 1.00); Categorical: Data NR, p=NS; [underlined: Obesity @ 42 y (OR (95% CI)]; Age at introduction to eggs; Continuous: 1.06 (0.96, 1.18); Categorical: Data NR, p=NR; Age at introduction to meat; Continuous: 0.97 (0.87, 1.08); Categorical: Data NR, p=NR | [underlined: Key confounders accounted for:] SEP; sex; milk feeding practices; gestational age; [underlined: Key confounders NOT accounted for:] race and/or ethnicity; baseline anthropometry; [underlined: Model adjustments:] Duration of BF, sex, maternal age at birth, prepregnancy BMI, gestational weight gain, smoking during pregnancy, social class, breadwinner’s education, single mother status, prematurity, birth weight, weight at 1 y (analysis of BMIZ for timing of any only), BMI (analysis of waist circumference only); [underlined: Funding:] NICHD; NIDA; The Danish Research Council; Danish National Board of Health; The National Danish Science Foundation; The National Danish Agricultural and Veterinary Research Council
Woo, 2013 (https://pubmed.ncbi.nlm.nih.gov/23236024/)^8^; PCS, GEHM, China, Mexico, U.S.; [underlined: Analytic N] = 285 (Excluded participants who were lost to follow-up); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race and/or ethnicity:] NR (Country: China: ~36%, Mexico: ~31%, U.S.: ~32%); [underlined: Maternal education:] China, Mexico, U.S., respectively: ≤HS graduate: 18.3%, 93.2%, 5.0%, Attended or graduated from college: 72.5%, 5.9%, 78.3%, Post-college education: 9.2%, 0.8%, 16.7%; [underlined: Other SEP measure(s):] Employed at time of pregnancy: 71.4% (China), 40.7% (Mexico), 80.8% (U.S.); WIC (U.S.): ~34%, Nutrisano supplemental food program (Mexico): 0%, Supplemental food programs in Shanghai (China): 0%; [underlined: Maternal age:] 29.3 (3.7) y (China), 24.4 (5.6)y (Mexico), 31.5 (5.2) y (U.S.); [underlined: Milk feeding practices:] EBF duration (median (IQR)): China: 4.9 (1.6, 11.9) wk, Mexico: 7.1 (0.0, 18.0) wk, U.S.: 13.7 (4.6, 19.3) wk; BF duration (median): China: 37.1 wk, Mexico: 52.0 wk, U.S.: 49.5 wk; [underlined: Child sex (female):] 49%; [underlined: Birth weight:] ~3.4 kg; [underlined: Gestational age:] 100% ≥37 wk gestation | [underlined: Exposure(s) and comparator(s):] High-protein foods (e.g., egg, meat, fish, legumes; continuous (mo)); [underlined: Dietary assessment methods:] Maternal 24 h food frequency recall via telephone.; [underlined: Age(s) at dietary assessment:] 2–52 wk, weekly; [underlined: Age of introduction:] Median (IQR) for China, Mexico, and U.S., respectively (mo): 4.8 (4.3, 5.4), 7.0 (6.3, 7.5), 9.3 (8.1, 10.5); [underlined: Outcome(s):] WAZ, LAZ, BMIZ; [underlined: Outcome assessment methods:] Weight and length measured by trained study personnel. WAZ, LAZ, and BMIZ calculated using age- and sex-specific z-scores from the 2005 WHO infant growth standards.; [underlined: Age(s) at outcome assessment:] 1 y | [underlined: WAZ @ 1 y]; −0.04 (0.02), p>0.05 in adjusted model; [underlined: LAZ @ 1 y]; Data NR, p>0.05 in adjusted model; [underlined: BMIZ @ 1 y]; Data NR, p>0.05 in adjusted model | [underlined: Key confounders accounted for:] SEP; sex; milk feeding practices; gestational age; [underlined: Key confounders NOT accounted for:] race and/or ethnicity; baseline anthropometry; [underlined: Model adjustments:] EBF duration, mother’s age, gestational weight gain, infant sex, birth weight, cohort site; [underlined: Funding:] Mead Johnson Nutrition Inc; NIH/NICHD; NIH/NCRR (Institutional Clinical and Translational Science Award)

a Abbreviations: @: at; β: beta; BF: breast feeding; BMI: body mass index; BMIZ: BMI z-score; CDC: Centers for Disease Control and Prevention; CI: confidence interval; cm: centimeter; d: day; EBF: exclusive breast feeding; EAT: Enquiring About Tolerance; FFQ: food frequency questionnaire; g: gram; GEHM: Global Exploration of Human Milk; h: hour; HAZ: height-for-age z-score; HC: head circumference; HCZ: head circumference z-score; HS: high school; IFPS II: Infant Feeding Practices Study II; IQR: interquartile range; kg: kilogram; LAZ: length-for-age z-score; mm: millimeter; mo: month; MUAC: mid-upper arm circumference; MUACZ: MUAC z-score; NR: not reported; NS: non-significant; OR: odds ratio; PCS: prospective cohort study; RCT: randomized controlled trial; ref: reference; RR: relative risk; SD: standard deviation; SEP: socioeconomic position; U.K.: United Kingdom; U.S.: United States; WAZ: weight-for-age z-score; WC: waist circumference; WHO: World Health Organization; WHZ: weight-for-height z-score; WIC: Special Supplemental Nutrition Program for Women, Infants, and Children; wk: week; WLZ: weight-for-length z-score; y: year

Table 19 Risk of bias for observational studies examining timing of protein foods and growth, body composition, and risk of obesity ^a^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Choudhary, 2023^9^ | SOME CONCERNS | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Mi, 2022^10^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | HIGH
Schack-Nielsen, 2010^5^ (All time points except 42 y) | SOME CONCERNS | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Schack-Nielsen, 2010^5^ (42 y time point) | SOME CONCERNS | SOME CONCERNS | LOW | LOW | HIGH | SOME CONCERNS | SOME CONCERNS | HIGH
Woo, 2013^8^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | LOW | LOW | HIGH | HIGH

a Possible ratings of low, some concerns, high, very high, no information, or not applicable determined using the "Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)" tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602. ) *Low risk of bias except for concerns about uncontrolled confounding.

### Dairy and fortified soy alternatives

#### Description of the evidence

Eleven studies from 13 articles^1,6,8,11–20^ met the inclusion criteria and examined the relationship between timing of the first introduction of dairy among infants and young children, up to age 24 months, and growth, body composition, or risk of obesity (Table 21). All 11 studies were PCS, using data from the following cohorts: Better Beginnings, Better Futures,^17,19^ Bogalusa Heart Study,^14^, Early Childhood Longitudinal Study,^15,1^,^6^ GEHM,^8^ Småbørns Kost og Trivsel,^13^ TARGet Kids!,^20^ Western Australian Pregnancy Cohort Study (Raine) cohort,^11^ WIC ITFPS-2,^6^ and 3 unnamed cohorts.^1,12,18^.

##### Population

Six studies were conducted in the United States,^1,6,8,12,14–1^,^6^ 2 were conducted in Canada,^17,19,20^, and 1 each were conducted in Australia,^11^ Denmark,^13^ Chile,^1^,^8^ China,^8^ and Mexico.^8^ The analytic sample sizes ranged from 68^1^ to 8,373,^18^ with the majority of studies having a sample size of 2,000 or less.^1,6,8,11–14,17,19,20^ One study reported that the analysis did not have sufficient power,^13^ while the remaining studies did not report power calculations related to timing of introduction of dairy and the relevant outcomes.^1,6,8,11,12,14–20^

Six studies provided information on the racial and/or ethnic background of participants; this varied across studies.^1,6,12,14–1^,^6,20^ Specifically, 100% of participants were Hispanic in 1 study,^1^ 41% Hispanic, 29% non-Hispanic White, 25% non-Hispanic African American, and 6% non-Hispanic other in another,^6^ 72% White, 15% Hispanic, 9% Black, 4% Asian in another,^12^ approximately 59% White and 41% Black in another,^14^ approximately 54% White, 25% Latino, and 14% African American, 4% multiracial, 3% Asian/Pacific Islander, and 0.4% American Indian/Alaska Native in another,^15,16^ and 67% European, 14% Asian, 5% mixed, 3% Hispanic, and 3% African in the last study.^20^ Across the 5 studies that reported maternal age,^1,6,8,12,17,19^ average age of the mothers ranged from mid-twenties to early thirties. Human milk and formula feeding practices were reported in 8 studies^1,6,8,12–17,19^ and tended to vary. First, breast feeding initiation was 75%^17,19^ and 81.9%^6^ in the 2 studies that reported this measure. Exclusive breastfeeding was assessed across infancy in 5 studies: in 1 study 51% were exclusively breast feeding at 1 month,^1^ 27% were exclusively breast feeding at 3 months in a second study,^17^ and at 4 months 53%^12^ and 68%^13^ of participants were exclusively breast feeding in a third and fourth study; the median duration of exclusive breastfeeding in the fifth study was 4.9 weeks in China, 7.1 weeks in Mexico, and 13.7 weeks in the U.S.^8^ Finally, any breastfeeding rates at 3 months ranged from 33.3%^17^ to 44%,^19^ at 6 months was 1%,^14^ 9 months was 42.5%,^13^ at 10 months was 20.8%,^1^ and mean or median duration ranged from approximately 3.7 months^15^ to 52 weeks.^8^

A variety of measures of SEP were reported across the studies. Maternal education was reported across 7 studies,^1,6,8,11–13,17,19^ showing that participants tended to have greater than a high school education level in most studies,^1,6,8,11,13,19^ although two studies included participants that tended to have less than a high school education level.^8,17^ One of these studies analyzed a subset of a larger sample^19^ of those who had a household income below the Statistics Canada low income cutoff.^17^ Two studies exclusively enrolled individuals participating in WIC,^1,6^ while 8 additional studies reported on family income,^6,8,11–13,15–17,19,20^ with several studies including a large proportion of participants with lower income.^6,15–17,19^

Regarding the characteristics of the infants and young children, the studies noted that approximately 50% of participants were female.^1,6,8,11–13,15–20^ Mean birth weight ranged from approximately 3.3 to 3.5 kilograms in 5 studies,^8,12,15–17,19,20^ while 1 study reported that 93.4% weighed between 2.5 and 4.5 kilograms at birth.^6^ Baseline anthropometry was reported in 3 studies^13–16^: average WHZ at age 5 months was −0.40 in 1 study,^13^ weight at age 6 months was significantly lower among infants consuming soy formula compared to infants consuming either cow’s milk or milk formula in a second study,^14^ and approximately 29% of the sample had a weight-for-length greater than or equal to the 85th percentile at age 9 months.^15,16^ Among the 7 studies that reported gestational age, 5 exclusively enrolled term infants,^6,8,11–13^ 1 study reported a mean gestational age of approximately 39 weeks,^15,1^,^6^ and 1 study exclusively enrolled infants born at least 32 weeks gestation.^20^

##### Exposures and comparators

Eight studies^1,6,13–20^ examined timing of introduction of cow’s milk, including 1 study that examined timing of introduction of powdered and fortified whole cow’s milk.^18^ The remaining studies examined timing of introduction of nonhuman milk more broadly, including “any milk other than breast milk”,^11^ “other” milks (including cow’s milk),^12^ and nonhuman milk (e.g., cow or soy milk),^8^ as well as nonmilk dairy foods (e.g., yogurt, fermented milk, cheese).^8^ Timing of introduction of dairy was analyzed in various ways across the studies. Three studies examined timing of introduction continuously,^11,15,1^,^6,20^ 6 studies examined timing of introduction categorically,^1,6,8,14,17–19^ and 2 studies did not report whether timing was analyzed as a continuous or categorical variable.^12,13^ Among the studies analyzing timing of introduction categorically, 3 studies used a cut point at age 12 months,^1,6,8^ 1 study compared the duration of consuming cow’s milk assessed at age 6 months (1, 3, 4.5 or 5.5 months duration),^14^ 1 study compared introduction between age 3 and 6 months or introduction after age 6 months to introduction before age 3 months,18 and a final study examined adherence to cow’s milk recommendations including both introduction of whole cow’s milk at or later than age 9 months and low-fat cow’s milk at or later than age 2 years.^17,19^ The studies used a variety of assessment methods to measure timing of introduction of dairy. The most common dietary assessment method was parental interview or questionnaire which was used 7 studies,^1,11,13–17,19,20^ while the remaining studies used a 24-hour dietary recall,^6^ 24-hour food frequency recall,^8^ 3-day food records and infant feeding history,^12^ and parental report at medical check-ups.^18^ Nine of the studies assessed timing of introduction of dairy multiple times from birth up to age 24 months.^1,6,8,11–14,17–19^ The assessments were conducted through age 12 months in 9 studies,^1,6,8,11–14,17–19^ while 7 studies included assessments beyond age 12 months.^1,6,12,13,17–20^

##### Outcomes

Seven studies assessed growth,^6,8,11,12,14,18,20^ 3 studies assessed body composition,^12–14^ and 4 studies assessed risk of obesity.^1,15–18^ A variety of outcomes related to growth were measured across the studies including BMIZ,^6,20^ BMI,^11^ WLZ,^12^ weight,^14^ WAZ,^8,12^ length,^14^ LAZ,^8,12^, HAZ,^20^ and circumferences of the head, chest, arm, and thighs.^12^ The measures of body composition also varied across the studies and included skinfold thickness,^12,14^ fat and fat-free mass percentages,^12^ and fat and fat-free mass index scores.^13^ The age at which the outcomes were assessed ranged from birth through age 8 years. The outcomes were measured by research staff or nurses across all studies.

#### Synthesis of the evidence

Across the 11 studies (Table 21), most reported predominantly or exclusively null associations between the timing of introduction of dairy with measures of growth, body composition, and risk of overweight or obesity, although 3 of these studies also reported significant associations between later introduction and lower levels of growth or risk of obesity in addition to null associations.^6,18,20^ Among the null findings, studies reported null associations between timing of introduction of cow’s milk,^1,6,13–16,20^ adherence to milk recommendations,^17,19^ any milk other than breast milk,^11^ “other” milks including cow’s milk,^12^ nonhuman milk,^8^ and nonmilk dairy foods8 and a variety of outcomes related to growth,^6,8,11,12,14,20^ body composition,^12–14^ and risk of overweight or obesity.^1,15–17,19^ Of these, only 3 studies reported the directionality of the null associations; the direction of these results tended to show greater BMIZ or greater odds of overweight or obesity with earlier introduction to cow’s milk.^14,19,20^

Although 11 studies examined the relationship between timing of introduction of dairy and growth, body composition, or risk of obesity, there were important concerns related to consistency that limited the ability to draw conclusions. Specifically, there was considerable heterogeneity in the exposures and comparators, particularly the timing of the exposures. The studies examined a wide range of time points of introduction from birth up to age 24 months, including 2 studies that specifically examined introduction cow’s milk early in infancy.^14,18^ Additionally, while some studies examined categories of introduction, some studies considered timing of introduction continuously. Several studies did not report how the timing variable was analyzed, be it categorically or continuously. In addition to the issues of consistency, there was minimal evidence for certain exposures and outcomes; in particular, dairy foods beyond cow’s milk as an exposure and body composition as an outcome.

#### Conclusion statement and grade

The Committee did not draw a conclusion statement about the relationship between timing of introduction of dairy in infants and young children, up to age 24 months, and growth, body composition, and risk of obesity because there is not enough evidence, and the evidence that is available has substantial concerns with consistency (Table 20). Studies assessed timing of the introduction of dairy, including cow’s milk at various time points, including 3, 6, and 12 months, and continuously. Several studies did not report how they analyzed the exposure timing variable. Therefore, it was difficult to compare across studies. There was minimal evidence for certain exposures and outcomes. Publication bias was also a consideration; however, this was not assessed as a serious concern because the body of evidence predominantly included studies that reported only nonsignificant findings, as well as studies that reported a mix of both significant and nonsignificant results, across a range of analytic sample sizes. However, while the literature search was comprehensive, a search of the gray literature was not done, which could increase the possibility of publication bias. The risk of bias assessments for this body of evidence are documented in Table 22.

Table 20 Conclusion statement, grade for timing of introduction of dairy and growth, body composition, and risk of obesity

Conclusion Statement | A conclusion statement cannot be drawn about the relationship between the age when infants and young children, up to age 24 months, are introduced to the dairy food group and outcomes related to growth patterns, body composition, and risk of obesity during childhood because there is not enough evidence available, and the evidence that is available has substantial concerns with consistency.
Grade | Grade Not Assignable
Body of Evidence | 13 articles (11 studies): 11 prospective cohort studies
Rationale | The studies varied in the exposures and comparators, particularly the timing of the exposures.

Table 21 Evidence examining the relationship between the timing of introduction to dairy and growth, body composition, and risk of obesity ^a^

Study and Participant Characteristics | Exposure, Comparator, and Outcome | Results | Key Confounders, Model Adjustments, Funding
Amaro-Rivera, 2019 (https://pubmed.ncbi.nlm.nih.gov/31260549/)^1^; PCS, U.S. (Puerto Rico); [underlined: Analytic N =] 68 (Excluded participants lost to follow-up); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race and/or ethnicity:] Hispanic: 100%; [underlined: Maternal education:] ≤HS: 32.5%, >HS: 67.5%; [underlined: Other SEP measure(s):] WIC participation: 100%; [underlined: Maternal age:] Parent’s age: <30 y: 55.8%, ≥30 y: 44.2%; [underlined: Milk feeding practices:] EBF for ≥1 mo: 51%, Ever FF: 70.1%, Any BF at ~10 mo: 20.8%; [underlined: Child sex (female):] 47%; [underlined: Birth size:] NR; [underlined: Gestational age:] NR | [underlined: Exposure(s) and comparator(s):] Timing of introduction to cow’s milk: <12 mo vs ≥12 mo; [underlined: Dietary assessment methods:] Interviewer-administered questionnaire completed by caregivers. Diet Quality Index Score based on semi-quantitative FFQ.; [underlined: Age(s) at dietary assessment:] 0–24 mo; [underlined: Age of introduction:] Cow’s milk: <12 mo: 18.2%; [underlined: Outcome(s):] WLZ (≥1); [underlined: Outcome assessment methods:] Weight and length measured by trained research staff. Weight status assessed using WHO age- and sex-specific WLZ growth charts. Relative risk for WLZ (≥1 z-score vs <1 z-score), with underweight defined as WLZ ≤-2 SD, healthy weight status defined as WLZ >-2 and <1 SD, risk of overweight defined as WLZ between 1-<2, and overweight or obesity defined as WLZ ≥2 SD.; [underlined: Age(s) at outcome assessment:] 11–36 mo (Median: 21 mo, 11–23 mo: 61.0%, 24–36 mo: 39.0%) | [underlined: WLZ (≥1 vs <1) @ 11–36 mo] <12 mo vs ≥12 mo: Data NR, NS | [underlined: Key confounders accounted for:] SEP; sex; race and/or ethnicity; milk feeding practices; baseline anthropometry; [underlined: Key confounders NOT accounted for:] gestational age; [underlined: Model adjustments:] WLZ at baseline; [underlined: Funding:] University of Puerto Rico Central Administration Grant; Capacity Advancement in Research Infrastructure; National Institute on Minority Health and Health Disparities
Au, 2023 (https://pubmed.ncbi.nlm.nih.gov/36806452/)^6^; PCS, WIC ITFPS-2, U.S.; [underlined: Analytic N =] 1,523 (24 mo), 1,680 (36 mo), 1,872 (48 mo) (Excluded participants with missing data on HEI-2015 or BMI at 2, 3, or 4y, born prematurely, had very low birth weight, or had long-term medical problems that could affect eating.); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race and/or ethnicity:] Hispanic: 40.6%, Non-Hispanic White: 29.1%, Non-Hispanic African American: 24.8%, Non-Hispanic Other: 5.5%; [underlined: Maternal education:] <HS: 24.4%, HS: 37.7%, >HS: 37.5%; [underlined: Other SEP measure(s):] Participating in WIC: 100%; Maternal employment at 6 mo: Full-time: 21.5%, Part-time: 20.2%, Not working for pay: 58.2%; Poverty level at enrollment: ≤75% of poverty guideline: 64.0%, >75-<130%: 26.3%, >130% poverty: 9.7%; [underlined: Maternal age:] 16–19 y: 11.7%, 20–25 y: 41.1%, ≥26 y: 47.3%; [underlined: Milk feeding practices:] Any BF: 81.9%; Any formula use: 95.5%; [underlined: Child sex (female):] 49%; [underlined: Birth weight:] Low (<2.5 kg): 5.3%, Normal (2.5-≤4.5 kg): 93.4%, High (>4.5 kg): 1.3%; [underlined: Gestational age:] Excluded infants born prematurely | [underlined: Exposure(s) and comparator(s):] Cow’s milk (Categorical, Infant Diet Quality Index component score from 0–1 based on degree of adherence to guidelines; max score: introduced at ≥12 mo, min score: introduced at <12 mo); [underlined: Dietary assessment methods:] 24-h dietary recall via telephone interview with caregiver; [underlined: Age(s) at dietary assessment:] 1, 3, 5, 7, 9 11, 13, 15, 18, 24, 30, 36, 42, and 48 mo; [underlined: Age of introduction:] ≥12 mo: 61.5%; [underlined: Outcome(s):] BMIZ; [underlined: Outcome assessment methods:] Weight and length/height collected at WIC sites or from child’s health care provider. BMIZ based on CDC age- and sex-specific growth charts; [underlined: Age(s) at outcome assessment:] 2, 3, 4 y | [underlined: BMIZ @ 2, 3, 4 y]; 2 y: Data NR, p>0.10; 3 y: Data NR, p>0.10; 4 y: greater adherence associated with lower BMIZ, p<0.05 | [underlined: Key confounders accounted for:] SEP; sex; gestational age; [underlined: Key confounders NOT accounted for:] race and/or ethnicity; milk feeding practices; baseline anthropometry; [underlined: Model adjustments:] None; [underlined: Funding:] NHLBI; USDA/NIFA
Burke, 2005 (https://pubmed.ncbi.nlm.nih.gov/15314630/)^11^; PCS, Western Australian Pregnancy Cohort Study (Raine), Australia; [underlined: Analytic N =] 1,430 (Excluded participants from multiple births, born before 37 wk gestation, with congenital abnormalities, and/or with missing outcome data at 8 y.); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race and/or ethnicity:] NR; [underlined: Maternal education:] Secondary: 46%, Diploma/other: 33%, Tertiary: 21%; [underlined: Other SEP measure(s):] Family income: ≤$40,000: 45%, >$40,000: 55%; [underlined: Maternal age:] NR; [underlined: Milk feeding practices:] NR; [underlined: Child sex (female):] 48%; [underlined: Birth size:] NR; [underlined: Gestational age:] 100% ≥37 wk | [underlined: Exposure(s) and comparator(s):] Age of introduction to any milk other than breast milk (Continuous (mo)); [underlined: Dietary assessment methods:] Maternal questionnaire; [underlined: Age(s) at dietary assessment:] 1 y, 3 y; [underlined: Age of introduction:] NR; [underlined: Outcome(s):] BMI; [underlined: Outcome assessment methods:] Weight and height measured by research staff.; [underlined: Age(s) at outcome assessment:] 8 y | [underlined: BMI @ 8 y]; Not retained in final model via backwards selection, p=NS | [underlined: Key confounders accounted for:] sex; SEP; milk feeding practices; gestational age; [underlined: Key confounders NOT accounted for:] race and/or ethnicity; baseline anthropometry; [underlined: Model adjustments:] NA (not retained in final model via backwards selection; model adjusted for sex, maternal education and additional variables tested included birth weight, BF duration, mother’s BMI, father’s BMI, mother smoking status, mother diabetes, mother gestational diabetes, time watching TV, physical activity, fat intake, saturated fat intake, takeaways factor, bread, cereals factor); [underlined: Funding:] Raine Foundation and Healthway
Butte, 2000 (https://pubmed.ncbi.nlm.nih.gov/11099589/)^12^; PCS, U.S.; [underlined: Analytic N] = 72 (Excluded participants who relocated outside of the study area.); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race and/or ethnicity:] White: 72.4%, Hispanic: 14.5%, Black: 9.2%, Asian: 3.9% Maternal education: ~15.5 y; [underlined: Other SEP measure(s):] Family income: <$20,000: 8%, $20,000–34,999: 24%, $35,000–49,999: 17%, ≥$50,000: 51%; [underlined: Maternal age:] ~28.7 y; [underlined: Milk feeding practices:] EBF at 4 mo: ~53%;; [underlined: Exclusive FF at 4 mo:] ~47%; BF duration (among those who BF): 11.4 (5.8) mo; [underlined: Child sex (female):] 57%; [underlined: Birth weight:] ~3.4 kg; Birth length: ~50 cm; [underlined: Gestational age:] ~39 wk (100% born term) | [underlined: Exposure(s) and comparator(s):] “Other” milks (including cow’s milk) (continuous or categorical NR); [underlined: Dietary assessment methods:] Caretaker report of infant feeding history and weighed 3-d food records; [underlined: Age(s) at dietary assessment:] 3, 6, 12, 24 mo; [underlined: Age of introduction:] NR; [underlined: Outcome(s):] Fat mass, fat-free mass, skinfold thickness (triceps, subscapular, flank, quadriceps), circumferences (head, chest, arm, thigh), WAZ, LAZ, WLZ; [underlined: Outcome assessment methods:] Weight, length, circumferences measured by trained study personnel. WAZ, LAZ, and WLZ calculated using NCHS growth curves for children. Fat-free mass, fat mass, and % fat mass estimated using multicomponent body composition model, total body electric conductivity (0.5 and 24 mo only), and DXA (0.5, 12, 24 mo only); [underlined: Age(s) at outcome assessment:] 0.5, 3, 6, 9, 12, 18, 24 mo | [underlined: WAZ @ 3, 6, 9, 12, 18, 24 mo] (FF infants; NR if BF infants analyzed) Data NR, p=NS; [underlined: LAZ @ 3, 6, 9, 12, 18, 24 mo] (FF infants; NR if BF infants analyzed) Data NR, p=NS; [underlined: WLZ @ 3, 6, 9, 12, 18, 24 mo] (FF infants; NR if BF infants analyzed) Data NR, p=NS; [underlined: HC @ 3, 6, 9, 12, 18, 24 mo] (FF infants; NR if BF infants analyzed); Data NR, p=NS; [underlined: Chest circumference @ 3, 6, 9, 12, 18, 24 mo] (FF infants; NR if BF infants analyzed); Data NR, p=NS; [underlined: Arm circumference @ 3, 6, 9, 12, 18, 24 mo] (FF infants; NR if BF infants analyzed); Data NR, p=NS; [underlined: Thigh circumference @ 3, 6, 9, 12, 18, 24 mo] (FF infants; NR if BF infants analyzed); Data NR, p=NS; [underlined: Triceps skinfold thickness @ 3, 6, 9, 12, 18, 24 mo] (FF infants; NR if BF infants analyzed); Data NR, p=NS; [underlined: Subscapular skinfold thickness @ 3, 6, 9, 12, 18, 24 mo] (FF infants; NR if BF infants analyzed); Data NR, p=NS; [underlined: Flank skinfold thickness @ 3, 6, 9, 12, 18, 24 mo] (FF infants; NR if BF infants analyzed); Data NR, p=NS; [underlined: Quadriceps skinfold thickness @ 3, 6, 9, 12, 18, 24 mo] (FF infants; NR if BF infants analyzed); Data NR, p=NS; [underlined: Fat mass @ 3, 6, 9, 12, 18, 24 mo] (FF infants; NR if BF infants analyzed) Data NR, p=NS; [underlined: % fat mass @ 3, 6, 9, 12, 18, 24 mo] (FF infants; NR if BF infants analyzed); Data NR, p=NS; [underlined: Fat-free mass @ 3, 6, 9, 12, 18, 24 mo] (FF infants; NR if BF infants analyzed); Data NR, p=NS | [underlined: Key confounders accounted for:] sex; milk feeding practices; gestational age; baseline anthropometry; [underlined: Key confounders NOT accounted for:] SEP; race and/or ethnicity; [underlined: Model adjustments:] Baseline values of outcome (0.5 mo), feeding mode (BF or formula fed), sex, age at measurement, interactions between feeding mode, sex and age, current weight and length (analyses of fat mass, % fat mass, and fat-free mass only); [underlined: Funding:] USDA/ARS; Ross Laboratories donated formula
Ejlerskov, 2015 (https://pubmed.ncbi.nlm.nih.gov/26131962/)^13^; PCS, SKOT, Denmark; [underlined: Analytic N =] 233 (Excluded participants who did not have complete BIA, height, and weight data at 3 y); [underlined: Adequately powered:] No; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race and/or ethnicity:] NR; [underlined: Maternal education:] No education above school level: 4.3%, Trainee or vocational education: 7.7%, Short academic education <3 y: 12.0%, Academic education 3–4 y: 35.2%, Long academic education >4 y: 40.8%; [underlined: Other SEP measure(s):] Family income (Danish Kroner): <200,000: 4.3%, 200,000–399,999: 15.0%, 400,000–599,999: 15.0%, 600,000–799,999: 30.5%, >800,000: 33.0%, Unknown: 2.1%; [underlined: Maternal age:] NR; [underlined: Milk feeding practices:] Fully BF for 4 mo: 67.8%, Partially BF at 9 mo: 42.5%; [underlined: Child sex (female):] 52%; [underlined: WHO z-scores at birth (mean (range)):] WAZ: 0.48 (−1.98, 2.71), HAZ: 1.39 (−3.84, 4.29), WFH: −0.95 (−4.71, 2.54), BMIZ: −0.35 (−3.99, 2.63); [underlined: Gestational age:] 100% born term (37–42 wk) | [underlined: Exposure(s) and comparator(s):] Timing of introduction to cow’s milk (continuous or categorical NR); [underlined: Dietary assessment methods:] Maternal interview; [underlined: Age(s) at dietary assessment:] 9, 18, 36 mo; [underlined: Age of introduction:] NR; [underlined: Outcome(s):] FMI, FFMI; [underlined: Outcome assessment methods:] Fat mass index and fat free mass index measured using BIA. FMI and FFMI grouped into sex-specific quartiles; [underlined: Age(s) at outcome assessment:] 3 y | [underlined: FMI @ 3 y]; Data NR, p>0.05; [underlined: FFMI @ 3 y]; Data NR, p>0.05 | [underlined: Key confounders accounted for:] SEP; sex; milk feeding practices; gestational age; baseline anthropometry; [underlined: Key confounders NOT accounted for:] race and/or ethnicity; [underlined: Model adjustments:] sex, birth weight z-score, WAZ change from 0 to 5 mo, educational level of mother, gestational weight gain, maternal BMI, duration of full BF; [underlined: Funding:] The Danish Directorate for Food, Fisheries and Agri Business
Farris, 1982 (https://pubmed.ncbi.nlm.nih.gov/7064877/)^14^; PCS, Bogalusa Heart Study, U.S.; [underlined: Analytic N =] 160 (Excluded participants without outcome measurements at 6 mo or 1 y and consuming multiple milk sources); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race and/or ethnicity:] White: ~59%, Black: ~41%; [underlined: Maternal education:] NR; [underlined: Other SEP measure(s):] NR; [underlined: Maternal age:] NR; [underlined: Milk feeding practices:] BM at 6 mo: 1%, Soy-based formula at 6 mo: 7%, Milk-based formula at 6 mo: 42%; [underlined: Child sex (female):] NR; [underlined: Birth size:] NR; [underlined: Gestational age:] NR | [underlined: Exposure(s) and comparator(s):] Duration of consuming cow’s milk at 6 mo: 1 mo vs 3 mo vs 4.5 mo vs 5.5 mo); [underlined: Dietary assessment methods:] Infant Feeding Practices Questionnaires and dietary questionnaires completed by mothers; [underlined: Age(s) at dietary assessment:] 1, 2, and 4 mo (infant feeding practices questionnaires); 6 mo and 1 y (dietary questionnaires); [underlined: Age of introduction:] Duration of consuming cow’s milk at 6 mo: 1, 3, 4.5, 5.5 mo, respectively: 55%, 29%, 11%, 5%; [underlined: Outcome(s):] Length, weight, skinfold (subscapular); [underlined: Outcome assessment methods:] Weight, length and skinfolds measured by trained personnel; [underlined: Age(s) at outcome assessment:] 6 mo, 1 y | [underlined: Weight (kg) @ 6 mo (mean (2 SE))]; Duration of cow’s milk consumption at 6 mo (among infants consuming cow’s milk): 1 mo vs 3 mo vs 4.5 mo vs 5.5 mo 7.7 (0.2) vs 7.6 (0.3) vs 7.8 (0.4) vs 7.5 (0.5), p=NS; [underlined: Length (cm) @ 6 mo (mean (2 SE))]; Duration of cow’s milk consumption at 6 mo (among infants consuming cow’s milk): 1 mo vs 3 mo vs 4.5 mo vs 5.5 mo 66.8 (0.6) vs 66.2 (0.8) vs 67.0 (1.4) vs 65.6 (1.6), p=NS; [underlined: Subscapular skinfold (mm) @ 6 mo (mean (2 SE))]; Duration of cow’s milk consumption at 6 mo (among infants consuming cow’s milk): 1 mo vs 3 mo vs 4.5 mo vs 5.5 mo 7.8 (0.4) vs 7.5 (0.7) vs 7.4 (0.8) vs 7.6 (1.4), p=NS | [underlined: Key confounders accounted for:] sex; race and/or ethnicity; [underlined: Key confounders NOT accounted for:] SEP; milk feeding practices; gestational age; baseline anthropometry; [underlined: Model adjustments:] None; [underlined: Funding:] National Heart and Lung Institute of the U.S. Public Health Service; Specialized Center of Research-Arteriosclerosis at Louisana State University Medical Center
Flores, 2013a (https://pubmed.ncbi.nlm.nih.gov/23553169/)^15^; PCS, ECLS-B, U.S.; [underlined: Analytic N =] 6,800 (Excluded participants who did not complete data collection during kindergarten or did not have complete age- and sex-specific BMI data.); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race and/or ethnicity:] White: ~54%, Latino: ~25%, African American: ~14%, Multiracial: ~3.8%, Asian/Pacific Islander: ~2.7%, American Indian/Alaska Native: ~0.4%; [underlined: Maternal education:] NR (Highest educational attainment in household: Not a HS graduate: ~13%, HS graduate: ~25%, At least some college: ~62%); [underlined: Other SEP measure(s):] Family income ever below poverty threshold: ~69%; Child’s insurance coverage: Uninsured: ~4%, Private: ~57%, Medicaid: ~34%, CHIP: ~4%, Military health care: ~1%, Indian health service: ~0.1%, Other government program: ~1%; [underlined: Maternal age:] NR; [underlined: Milk feeding practices:] BF duration: ~3.7 mo; [underlined: Child sex (female):] ~49%; [underlined: Birth weight:] ~3,300 g; [underlined: Gestational age:] ~38.7 wk | [underlined: Exposure(s) and comparator(s):] Age first fed cow’s milk (Continuous); [underlined: Dietary assessment methods:] Maternal interview; [underlined: Age(s) at dietary assessment:] NR; [underlined: Age of introduction:] NR; [underlined: Outcome(s):] Overweight; [underlined: Outcome assessment methods:] Height and weight measured by study field interviewers. Overweight defined as BMI ≥85th percentile according to CDC growth charts.; [underlined: Age(s) at outcome assessment:] At entry to kindergarten (~5.7 y) | [underlined: Overweight @ entry to kindergarten]; Data NR, p=NS | [underlined: Key confounders accounted for:] sex; [underlined: Key confounders NOT accounted for:] SEP; race/ethnicity; milk feeding practices; gestational age; baseline anthropometry; [underlined: Model adjustments:] NA (only examined in bivariate analyses); [underlined: Funding:] No funding received for study
Flores, 2013b (https://pubmed.ncbi.nlm.nih.gov/23147114/)^16^; PCS, ECLS-B, U.S.; [underlined: Analytic N =] 6,800 (Reasons for attrition NR); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race and/or ethnicity:] White: ~54%, Latino: ~25%, African American: ~14%, Multiracial: ~3.8%, Asian/Pacific Islander: ~2.7%, American Indian/Alaska Native: ~0.4%; [underlined: Maternal education:] NR (Highest educational attainment in household: Not a HS graduate: ~13%, HS graduate: ~25%, At least some college: ~62%); [underlined: Other SEP measure(s):] Family income ever below poverty threshold: ~69%; Child’s insurance coverage: Uninsured: ~4%, Private: ~57%, Medicaid: ~34%, CHIP: ~4%, Military health care: ~1%, Indian health service: ~0.1%, Other government program: ~1%; [underlined: Maternal age:] NR; [underlined: Milk feeding practices:] Age first fed formula: ~3.6 mo; [underlined: Child sex (female):] ~49%; [underlined: Birth weight:] ~3,300 g; [underlined: Gestational age:] ~38.7 wk | [underlined: Exposure(s) and comparator(s):] Age first fed cow’s milk (Continuous); [underlined: Dietary assessment methods:] Maternal interview; [underlined: Age(s) at dietary assessment:] NR; [underlined: Age of introduction:] NA; [underlined: Outcome(s):] Severe obesity; [underlined: Outcome assessment methods:] Height and weight measured by study field interviewers. Definition of severe obesity not provided.; [underlined: Age(s) at outcome assessment]: At entry to kindergarten (~5.7 y) | [underlined: Severe obesity @ entry to kindergarten]; Data NR, p=NS | [underlined: Key confounders accounted for:] sex; [underlined: Key confounders NOT accounted for:] SEP; race/ethnicity; milk feeding practices; gestational age; baseline anthropometry; [underlined: Model adjustments:] NA (only examined in bivariate analyses); [underlined: Funding:] NR
Kuperberg, 2006 (https://pubmed.ncbi.nlm.nih.gov/16759434/)^17^; PCS, Better Beginnings, Better Futures, Canada; [underlined: Analytic N =] 71 (Excluded participants without outcome data, and potentially without exposure data. Excluded infants with birth weight <2,500 g.); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race and/or ethnicity:] NR (100% of children living in First Nations community – Ojibwa, Potawatom, and Ottawa bands); [underlined: Maternal education:] <HS education: 63.4%; [underlined: Other SEP measure(s):] 100% with household income below Statistics Canada low income cutoff; [underlined: Maternal age:] 25.4 (6.8) y; [underlined: Milk feeding practices:] Initiated BF: 75%, EBF at 3 mo: 27.0%, partially BF at 3 mo: 33.3%; [underlined: Child sex (female):] 49%; [underlined: Birth weight:] 3,396 (652) g; [underlined: Gestational age:] NR | [underlined: Exposure(s) and comparator(s):] Adherence to cow’s milk recommendations (whole cow’s milk ≥9 mo, low-fat cow’s milk ≥2 y) vs non-adherence to cow’s milk recommendations (ref)); [underlined: Dietary assessment methods:] Maternal interview; [underlined: Age(s) at dietary assessment:] 3 mo, 18 mo, 33 mo; [underlined: Age of introduction:] Whole cow’s milk <9 mo: 11.6%, Low-fat cow’s milk <2 y: 59.4%; [underlined: Outcome(s):] Overweight; [underlined: Outcome assessment methods:] Weight and height measured using standard procedures. Overweight defined as BMI at or above 85th percentile according to age- and sex-specific reference data (NCHS).; [underlined: Age(s) at outcome assessment:] 48 mo | [underlined: Overweight @ 48 mo]; Adherence to cow’s milk recommendations (whole cow’s milk ≥9 mo, low-fat cow’s milk ≥2 y); Data NR, p=NS | [underlined: Key confounders accounted for:] race and/or ethnicity; SEP; sex; milk feeding practices; [underlined: Key confounders NOT accounted for:] gestational age; baseline anthropometry; [underlined: Model adjustments:] NR (unclear whether univariate or multivariate regression was completed); [underlined: Funding:] Ontario Ministries of Health and Long-Term Care, Community and Social Services, and Education
Retamal, 2020 (https://pubmed.ncbi.nlm.nih.gov/32457472/)^18^; RCS, Chile; [underlined: Analytic N =] 8,373 (Excluded participants with missing data.); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race and/or ethnicity:] NR; [underlined: Maternal education:] NR; [underlined: Other SEP measure(s):] NR; [underlined: Maternal age:] NR; [underlined: Milk feeding practices:] NR; [underlined: Child sex (female):] 49%; [underlined: Birth size:] NR; [underlined: Gestational age:] NR | [underlined: Exposure(s) and comparator(s):] Whole cow’s milk (powdered and fortified with vitamin C, iron, zinc, and copper): <3 mo (ref), 3–6 mo, >6 mo; [underlined: Dietary assessment methods:] Parental report at routine medical check-ups; [underlined: Age(s) at dietary assessment:] Birth-3 y (~every 6 mo); [underlined: Age of introduction:] NR; [underlined: Outcome(s):] Change in WHZ, overweight, obesity; [underlined: Outcome assessment methods:] Height and weight from routine medical check-ups. WHZ based on WHO data and categorized as normal (WHZ > −1 and <1 SD), overweight (WHZ ≥1 and <2 SD), and obese (WHZ ≥2 SD).; [underlined: Age(s) at outcome assessment:] Birth, 6, 12, 18, 24, 30, 36 mo | [underlined: Change in WHZ from birth-12 mo, 18–36 mo, and birth-36 mo (mean)]; <3 vs 3–6 vs >6 mo; Birth-12 mo: 0.556 vs 0.486 vs 0.638, p<0.001; 18–36 mo: 0.968 vs 0.852 vs 0.860, p<0.001; Birth-36 mo: 0.791 vs 0.695 vs 0.765, p<0.001; [underlined: Overweight (>1 and <2 SD WHZ) @ birth-12 mo, 18–36 mo, and birth-36 mo (OR (95% CI))]; Birth-12 mo:; 3–6 mo vs <3 mo (ref): 0.919 (0.830, 1.016), p=NS; >6 mo vs <3 mo (ref): 1.104 (1.011, 1.206), p=0.027; 18–36 mo:; 3–6 mo vs <3 mo (ref): 0.851 (0.759, 0.954), p=0.005; >6 mo vs <3 mo (ref): 0.843 (0.761, 0.935), p=0.001; Birth-36 mo:; 3–6 mo vs <3 mo (ref): 0.886 (0.809, 0.970), p=0.009; >6 mo vs <3 mo (ref): 0.947 (0.873, 1.027), p=NS; [underlined: Obesity (>2 SD WHZ) @ birth-12 mo, 18–36 mo, and birth-36 mo (OR (95% CI))]; Birth-12 mo:; 3–6 mo vs <3 mo (ref): 0.759 (0.633, 0.911), p=0.003; >6 mo vs <3 mo (ref): 1.267 (1.092, 1.470), p=0.002; 18–36 mo:; 3–6 mo vs <3 mo (ref): 0.749 (0.633, 0.887), p=0.001; >6 mo vs <3 mo (ref): 0.823 (0.710, 0.956), p=0.011; Birth-36 mo:; 3–6 mo vs <3 mo (ref): 0.775 (0.666, 0.901), p=0.001; >6 mo vs <3 mo (ref): 0.962 (0.847, 1.093), p=NS | [underlined: Key confounders accounted for:] SEP; sex; milk feeding practices; [underlined: Key confounders NOT accounted for:] race and/or ethnicity; gestational age; baseline anthropometry; [underlined: Model adjustments:] County of birth, household occupation, birth order, sex, year of birth, age of giving other types of food, age of the mother at birth of child, age of BF cessation; [underlined: Funding:] Becas Chile Scholarship Program
Rossiter, 2013 (https://pubmed.ncbi.nlm.nih.gov/24018001/)^19^; PCS, Better Beginnings, Better Futures, Canada; [underlined: Analytic N =] 350 (Excluded participants lost to follow-up.); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race and/or ethnicity:] NR (Born outside Canada: 29%); [underlined: Maternal education:] Less than HS education: 39%; [underlined: Other SEP measure(s):] Living below low income cut-offs (Statistics Canada): 72%; [underlined: Maternal age:] 27 (5.9) y; [underlined: Milk feeding practices:] BF initiation: 75%, BF at 3 mo: 44%; [underlined: Child sex (female):] ~43%; [underlined: Birth weight:] ~3475 g (all >2,500 g); [underlined: Gestational age:] NR | [underlined: Exposure(s) and comparator(s):] Adherence to cow’s milk recommendations (whole cow’s milk ≥9 mo, low-fat cow’s milk ≥2 y), non-adherence to cow’s milk recommendations (ref)); [underlined: Dietary assessment methods:] Maternal interview; [underlined: Age(s) at dietary assessment:] 3, 18, 33, 48 mo; [underlined: Age of introduction:] Adherence to cow’s milk recommendations: ~39%, non-adherence to cow’s milk recommendations: ~61%; [underlined: Outcome(s):] Overweight/obesity; [underlined: Outcome assessment methods:] Height and weight measured using established guidelines. Overweight/obesity classified based on CDC sex- and age-specific growth tables.; [underlined: Age(s) at outcome assessment:] 48 mo | [underlined: Overweight/obesity @ 48 mo (%)]; Adherence to milk recommendations (introduction to cow’s milk >9 mo, introduction to low-fat milk >24 mo) vs not (ref); 1.81 (0.76, 4.30) | [underlined: Key confounders accounted for:] SEP; sex; [underlined: Key confounders NOT accounted for:] race/ethnicity; milk feeding practices; gestational age; baseline anthropometry; [underlined: Model adjustments:] sex, maternal age, poverty, smoking status, maternal BMI, single-parent household, birth weight; [underlined: Funding:] Ontario Ministries of Health and Long-Term Care, Community and Social Services, and Education
Soczynska, 2021 (https://pubmed.ncbi.nlm.nih.gov/32723404/)^20^; PCS, TARGet Kids!, Canada; [underlined: Analytic N =] 1,981 (Excluded participants who were not 3–5 y for outcome assessment, lost to follow-up, had not yet been introduced to cow’s milk at follow-up (3–5 y), or had missing data for age of cow milk introduction.); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race and/or ethnicity:] European: 66.8%, Asian: 14.2%, Mixed: 4.7%, Hispanic: 3.1%, African: 2.9%; [underlined: Maternal education]: NR; Other SEP measure(s): After tax family income (CAD): <$30,000: 3.4%, $30,000–79,999: 12.4%, $80,000–149,999: 32.9%, ≥$150,000: 47.2%; [underlined: Maternal age:] NR; [underlined: Milk feeding practices:] NR; [underlined: Child sex (female):] 46%; [underlined: Birth weight:] 3.31 (0.57) kg; Gestational age: 100% >32 wk | [underlined: Exposure(s) and comparator(s):] Timing of introduction to cow’s milk (Continuous (mo)); [underlined: Dietary assessment methods:] Parental questionnaire; [underlined: Age(s) at dietary assessment:] ≤2 y (Mean (SD): 16.9 (4.2) mo); [underlined: Age of introduction:] Mean (SD): 11.7 (2.1) mo (min: 4 mo, max: 30 mo); <9 mo: 3.6%, 9–11.9 mo: 28.4%, 12–12.9 mo: 56.9%, 13–17.9 mo: 8.6%, ≥18 mo: 2.4%; [underlined: Outcome(s):] HAZ, BMIZ; [underlined: Outcome assessment methods:] Height and weight measured by trained research assistants. Z-scores were calculated using 2006 WHO child growth standards.; [underlined: Age(s) at outcome assessment:] 3–5 y (Mean (SD): 46.9 (7.5) mo) | [underlined: HAZ @ 3–5 y (β (95% CI))]; −0.03 (−0.05, −0.02), p<0.001; Exploration of nonlinearity showed that age of cow milk introduction was associated with HAZ beginning after age 9 mo, p<0.05; [underlined: BMIZ @ 3–5 y (β (95% CI))]; 0.02 (0.00, 0.04), p=0.13 | [underlined: Key confounders accounted for:] SEP; sex; race and/or ethnicity; milk feeding practices; baseline anthropometry; [underlined: Key confounders NOT accounted for:] gestational age; [underlined: Model adjustments:] Age, sex, birth weight, BF duration, maternal ethnicity, household income, maternal height, SSB consumption, BMI and length-for-age z-score prior to the introduction of cow milk; [underlined: Funding:] No external funding
Woo, 2013 (https://pubmed.ncbi.nlm.nih.gov/23236024/)^8^; PCS, GEHM, China, Mexico, U.S.; [underlined: Analytic N =] 285 (Excluded participants who were lost to follow-up); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race and/or ethnicity:] NR (Country: China: ~36%, Mexico: ~31%, U.S.: ~32%); [underlined: Maternal education:] China, Mexico, U.S., respectively: ≤HS graduate: 18.3%, 93.2%, 5.0%, Attended or graduated from college: 72.5%, 5.9%, 78.3%, Post-college education: 9.2%, 0.8%, 16.7%; [underlined: Other SEP measure(s):] Employed at time of pregnancy: 71.4% (China), 40.7% (Mexico), 80.8% (U.S.); WIC (U.S.): ~34%, Nutrisano supplemental food program (Mexico): 0%, Supplemental food programs in Shanghai (China): 0%; [underlined: Maternal age:] 29.3 (3.7) y (China), 24.4 (5.6) y (Mexico), 31.5 (5.2) y (U.S.); [underlined: Milk feeding practices:] EBF duration (median (IQR)): China: 4.9 (1.6, 11.9) wk, Mexico: 7.1 (0.0, 18.0) wk, U.S.: 13.7 (4.6, 19.3) wk. BF duration (median): China: 37.1 wk, Mexico: 52.0 wk, U.S.: 49.5 wk; [underlined: Child sex (female):] 49%; [underlined: Birth weight:] ~3.4 kg; [underlined: Gestational age:] 100% ≥37 wk gestation | [underlined: Exposure(s) and comparator(s):] Nonhuman milk (e.g., cow or soy milk): Ever vs never introduced in the first y; Nonmilk dairy foods (e.g., yogurt, fermented milk, cheese): Ever vs never introduced in the first year; [underlined: Dietary assessment methods:] Maternal 24 h food frequency recall via telephone.; [underlined: Age(s) at dietary assessment:] 2–52 wk, weekly; [underlined: Age of introduction:] Median (IQR) for China, Mexico, and U.S., respectively (mo): Nonhuman milk: 11.8 (8.4, 12.1), 9.8 (8.1, 11.9), 11.7 (11.3, 12.1), Nonmilk dairy foods: 11.2 (7.3, 11.9), 8.9 (7.0, 11.1), 9.4 (8.1, 10.8); [underlined: Outcome(s):] WAZ, LAZ, BMIZ; [underlined: Outcome assessment methods:] Weight and length measured by trained study personnel. WAZ, LAZ, and BMIZ calculated using age- and sex-specific z-scores from the 2005 WHO infant growth standards.; [underlined: Age(s) at outcome assessment:] 1 y | [underlined: WAZ @ 1 y]; Nonhuman milk: Data NR, p≥0.20 Nonmilk dairy foods: Data NR, p≥0.20; [underlined: LAZ @ 1 y]; Nonhuman milk: Data NR, p≥0.20 Nonmilk dairy foods: Data NR, p≥0.20; [underlined: BMIZ @ 1 y]; Nonhuman milk: Data NR, p≥0.20 Nonmilk dairy foods: Data NR, p≥0.20 | [underlined: Key confounders accounted for:] SEP; sex; milk feeding practices; gestational age; [underlined: Key confounders NOT accounted for:] race and/or ethnicity; baseline anthropometry; [underlined: Model adjustments:] Cohort site; [underlined: Funding:] Mead Johnson Nutrition Inc; NIH/NICHD; NIH/NCRR (Institutional Clinical and Translational Science Award)

a Abbreviations: @: at; β: beta; BF: breast feeding; BIA: bioelectrical impedance analysis; BM: breast milk; BMI: body mass index; BMIZ: BMI z-score; CAD: Canadian Dollar; CDC: Centers for Disease Control and Prevention; CHIP: Children’s Health Insurance Program; CI: confidence interval; cm: centimeter; d: day; EBF: exclusive breast feeding; ECLS-B: Early Childhood Longitudinal Study; g: gram; FF: formula feeding; FFMI: fat-free mass index; FFQ: food frequency questionnaire; FMI: fat mass index; g: gram; GEHM: Global Exploration of Human Milk; h: hour; HAZ: height-for-age z-score; HS: high school; IQR: interquartile range; kg: kilogram; LAZ: length-for-age z-score; mm: millimeter; mo: month; NR: not reported; NS: non-significant; OR: odds ratio; PCS: prospective cohort study; ref: reference; SD: standard deviation; SE: standard error; SEP: socioeconomic position; SKOT: Småbørns Kost og Trivsel; SSB: sugar-sweetened beverage; TARGet Kids: The Applied research Group for Kids!; U.S.: United States; WAZ: weight-for-age z-score; WFH: weight-for-height/length z-score; WHO: World Health Organization; WHZ: weight-for-height z-score; WIC: Special Supplemental Nutrition Program for Women, Infants, and Children; WIC ITFPS-2: WIC Infant and Toddler Feeding Practices Study-2; wk: week; WLZ: weight-for-length z-score; y: year

Table 22 Risk of bias for observational studies examining timing of introduction to dairy and growth, body composition, and risk of obesity ^a^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Amaro-Rivera, 2019^1^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Au, 2023^6^ | HIGH | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Burke, 2005^11^ | SOME CONCERNS | HIGH | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Butte, 2000^12^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | LOW | LOW | HIGH | HIGH
Ejlerskov, 2015^13^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Farris, 1982^14^ | VERY HIGH | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | VERY HIGH
Flores, 2013a^15^ | LOW | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Flores, 2013b^16^ | LOW | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Kuperberg, 2006^17^ | SOME CONCERNS | HIGH | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Retamal, 2020^18^ | HIGH | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Rossiter, 2013^19^ | HIGH | HIGH | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Soczynska, 2020^20^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Woo, 2013^8^ | VERY HIGH | SOME CONCERNS | LOW | LOW | LOW | LOW | HIGH | VERY HIGH

a Possible ratings of low, some concerns, high, very high, no information, or not applicable determined using the "Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)" tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602. ) *Low risk of bias except for concerns about uncontrolled confounding.

### Sugar-sweetened beverages

#### Description of the evidence

Nine articles met inclusion criteria and examined the relationship between the timing of introduction of SSBs in infants and young children, up to age 24 months, and growth, body composition, and risk of obesity (Table 24).^3,4,6,8,21–25^ All 9 studies were PCS, using data from the following cohorts: Born in Bradford,^25^ Early Life Exposure in Mexico to Environmental Toxicants,^22^ GEHM,^8^ Impact of Perinatal Environmental Variations in the First 6 Months of Life,^21^ IFPS II,^2^,^3^ Project Viva,^4^ Upstate KIDS,^24^ WIC ITFPS-2,^6^ and 1 unnamed study.^3^

##### Population

Six studies were conducted in the United States,^3,4,6,8,2^,^3,24^ while the remaining studies were conducted in Brazil,^21^ China,^8^ Mexico,^8,22^ and the United Kingdom.^25^ The analytic sample sizes of the studies ranged from 943 to 2,056.^24^ The studies did not provide information regarding statistical power.

Race and/or ethnicity varied across the 7 studies that reported this information. Individuals who were White or non-Hispanic White were commonly included across studies, representing 29% to 100% of participants in all 7 studies.^3,4,6,21,2^,^3–25^ Individuals of other races and/or ethnicities were also included, but in generally smaller proportions, including individuals who were Hispanic (4% to 41% across 3 studies),^4,6,23^ Black or African American (3% to 25% across 4 studies),^4,6,21,23^ Asian (3%),4 and Pakistani (49%).^25^ Average maternal age tended to range from the mid-twenties to the early-thirties.^4,6,8,21–25^ Human milk feeding practices, and the metrics reported, varied across the studies. Three studies reported rates of ever breast feeding which ranged from 78% to 82%.^3,6,21^ Regarding human milk feeding duration, 3 studies provided information on breast feeding at 4 months with rates ranging from 59% to 69%,^3,4,24^ 2 studies provided information on breast feeding at 6 months with rates of 51% for any breast feeding^2^,^3^ and 12% for exclusive breast feeding,^3^ and 1 study provided information on partial breast feeding at 12 months reporting a rate of 31%.^22^ An additional study reported median durations of exclusive and any breast feeding which ranged from 4.9 to 13.7 weeks and 37.1 to 52.0 weeks, respectively, depending on the country the participants hailed from.^8^ Finally, 1 study noted that 32% of participants continued to breast feed after introducing solid foods.^25^ Measures of SEP were reported across all studies. The most common SEP measure was maternal education: several studies reported that relatively high percentages of individuals who attended college, graduated from college, or had an advanced degree,^3,4,8,2^,^3,24^ while some reported relatively lower levels of maternal education.^6,21,25^

The children enrolled in these studies were approximately 50% female. Three studies reported mean birth weight which ranged from 3.4 to 3.5 kilograms.^3,4,8^ Other studies reported that only a small proportion of participants had low^6,25^ or high^6,23^ birth weight. In 3 studies the participants were limited to those born term,^3,6,8^ while a fourth reported an average gestational age of 39.7 weeks,^4^ and a fifth reported that only 5% of participants were born preterm.^25^

##### Exposures and comparators

The beverages examined were in 2 primary categories: SSBs excluding 100% juice (such as sodas, soft drinks, and fruit drinks)^6,8,22,23,25^ and juice that was not defined by the study as 100% juice.^3,4,8,21,24^ Two studies examined age of introduction as a continuous variable,^3,8^ but most examined age of introduction as a categorical variable.^4,6,8,21–25^ The most common age cut points examined were 6 months^4,21,23,24^ and 12 months.^6,8,22–24^ Timing of introduction to SSBs was assessed primarily through maternal questionnaires,^4,21,23–25^ but other methods included 24-hour recalls,^3,6^ 24-hour food frequency recall,8 and a semi-quantitative food-frequency questionnaire (FFQ).^22^

##### Outcomes

Growth, body composition, and risk of obesity were assessed using a variety of measures. Outcomes related to growth were reported in 7 studies,^3,4,6,8,21,24,25^ with the most common outcome being BMIZ. Additional outcomes included weight, length, change in weight slope relative to length slope, WAZ, HAZ, and LAZ. Two studies examined measures of body composition, including waist circumference, body fat percentage, truncal fat mass, and skinfold thickness,^4,22^ and 4 studies examined the risk of overweight and/or obesity.^21–24^ Most studies reported that the outcomes were measured by study personnel,^3,4,6,8,21,22,25^ however 2 studies relied on maternal report of height and weight.^23,24^ Z-scores were calculated using growth standards from the WHO^8,21,22,25^ and the CDC.^4,6,23,2^,^4^ The outcomes were assessed at a variety of timepoints from infancy to adolescence: 2 studies assessed outcomes among infants and young children up to age 24 months,^3,8^ 6 studies assessed outcomes among children,^4,6,21–25^ and 2 studies assessed outcomes among adolescents.^4,22^

#### Synthesis of the evidence

Of the 9 studies that examined timing of introduction of SSBs (Table 24), 4 reported statistically significant, indirect associations between age at introduction and growth, body composition, or risk of obesity, although all also reported null associations between the exposure and outcomes depending on the specific outcome measure or timepoint analyzed.^4,6,23,2^,^4^ Of these, 2 assessed SSBs excluding juice, with 1 study reporting that introduction to SSBs at age 12 months or later was associated with lower BMIZ at age 4 years, but not at earlier ages (2 and 3 years),^6^ and the other reporting that introduction to SSBs prior to age 6 months compared to after age 12 months was associated with higher odds of obesity at age 6 years, while comparisons between introduction from age 6 to 12 months and after age 12 months in this study did not achieve statistical significance but were in the same direction.^23^ The other 2 studies examined juice that was not defined as being 100%. One reported that introduction to juice before age 6 months, compared to age 12 months or later, was associated with higher WAZ, BMIZ, and risk of obesity at age 7 to 9 years, while associations tended to be null at age 2 to 3 years and for the outcomes of risk of overweight and HAZ.^24^ The other reported that introduction to juice prior to age 4 months, compared to between age 4 and 6 months, was associated with greater BMIZ and waist circumference at age 8 years, but only among infants breastfed for at least 4 months; differences in these outcomes at age 13 years were not detected.^4^

The remaining 5 studies did not detect differences in outcomes related to growth, body composition, and risk of obesity by age of introduction to SSBs, 3 which assessed SSBs such as sweetened drinks and soft drinks^8,22,25^ and 3 which assessed juice which was not defined or could not be confirmed to be 100% juice.^3,8,21^ Two studies did not provide information on the direction or magnitude of the results beyond statistical significance,^3,8^ while the remaining studies reported non-significant associations that were both consistent^21,22^ and inconsistent^25^ with those of the statistically significant findings showing greater BMIZ, WAZ, and odds of obesity with earlier introduction, but these studies generally had a small magnitude or wide confidence intervals. A wide range of relationships were analyzed across these studies, including: introduction to SSBs at or before age 12 months and both obesity and abdominal obesity at age 8 to 14 years^22^; introduction to sweetened drinks prior to age 17 weeks and BMIZ at age 3 years^25^; introduction to soft drinks by age 1 year, as well as introduction to juice modeled continuously, and WAZ, LAZ, and BMIZ at age 1 year ^8^; introduction to juice prior to age 6 months and BMIZ and weight status at age 3 to 6 years^21^; and age of juice introduction modeled continuously and change in weight, length, and weight relative to length from age 2 to 8 months and age 12 to 24 months^3^

There was considerable heterogeneity in this body of evidence across multiple domains, limiting the ability to make meaningful comparisons and draw conclusions. First, although 9 studies were categorized as examining timing of introduction to SSBs, only 5 studies examined SSBs such as soda, soft drinks, and/or fruit drinks^6,22,23,25^ while 5 studies assessed timing of introduction to juice that was not defined as 100% juice or could not be confirmed to be querying introduction to 100% juice^3,4,8,21,2^,^4^; it is unknown to what extent the results of these studies reflect timing of introduction to 100% juice versus juice with added sugars. Second, timing of introduction was assessed both continuously^3,8^ and using a variety of categorical cut points across the studies, including at approximately age 4 months,^4,25^ age 6 months,^4,21,23,2^,^4^ and age 12 months.^6,8,22–24^ None of the studies examined timing cut points beyond age 12 months. Finally, the outcomes related to growth, body composition, and risk of obesity were assessed across a large range of ages, as young as 8 months^3^ and as old as 14 years.^22^

#### Conclusion statement and grade

The Committee did not draw a conclusion statement about the relationship between the timing of introduction of SSBs in infants and young children, birth up to 24 months, and growth, body composition, and risk of obesity (Table 23). This was due to considerable heterogeneity across the studies regarding the beverages included in the exposures and comparators, the timing cut points examined, and the age at which the outcomes were assessed. Publication bias was also a consideration; however, this was not assessed as a serious concern because the body of evidence included studies that reported only nonsignificant findings as well as studies that reported a mix of both significant and nonsignificant results, across a range of analytic sample sizes. However, while the literature search was comprehensive, a search of the gray literature was not done, which could increase the possibility of publication bias. The risk of bias assessments for the studies that addressed this question are documented in Table 25.

Table 23 Conclusion statement, grade for timing of introduction of sugar-sweetened beverages and growth, body composition, and risk of obesity

Conclusion Statement | A conclusion statement cannot be drawn about the relationship between the age when infants and young children, up to age 24 months, are introduced to sugar-sweetened beverages and outcomes related to growth patterns, body composition, and risk of obesity during childhood because of substantial concerns with consistency in the body of evidence.
Grade | Grade Not Assignable
Body of Evidence | 9 articles: 9 prospective cohort studies
Rationale | The studies had inconsistent exposures and comparators, including the timing cut points examined, as well as varied ages at outcome assessment

Table 24 Evidence examining the relationship between timing of introduction to sugar-sweetened beverages and growth, body composition, and risk of obesity ^a^

Study and Participant Characteristics | Exposure, Comparator, and Outcome | Results | Key Confounders, Model Adjustments, Funding
Au, 2023 (https://pubmed.ncbi.nlm.nih.gov/36806452/)^6^; PCS, WIC ITFPS-2, U.S.; [underlined: Analytic N] = 1,523 (24 mo), 1,680 (36 mo), 1,872 (48 mo) (Excluded participants with missing data on HEI-2015 or BMI at 2, 3, or 4 y, born prematurely, had very low birth weight, or had long-term medical problems that could affect eating.); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race and/or ethnicity:] Hispanic: 40.6%, Non-Hispanic White: 29.1%, Non-Hispanic African American: 24.8%, Non-Hispanic Other: 5.5% Maternal education: <HS: 24.4%, HS: 37.7%, >HS: 37.5%; [underlined: Other SEP measure(s):] Participating in WIC: 100%; Maternal employment at 6 mo: Full-time: 21.5%, Part-time: 20.2%, Not working for pay: 58.2%; Poverty level at enrollment: ≤75% of poverty guideline: 64.0%, >75–<130%: 26.3%, >130% poverty: 9.7%; [underlined: Maternal age:] 16–19 y: 11.7%, 20–25 y: 41.1%, ≥26 y: 47.3%; [underlined: Milk feeding practices:] Any BF: 81.9%; Any formula use: 95.5%; [underlined: Child sex (female):] 49%; [underlined: Birth weight:] Low (<2.5 kg): 5.3%, Normal (2.5-≤4.5 kg): 93.4%, High (>4.5 kg): 1.3%; [underlined: Gestational age:] Excluded infants born prematurely | [underlined: Exposure(s) and comparator(s):] Age of first introduction of SSB (soda, soft drinks or other sweetened beverages (Kool Aid, Hi-C, Fruit Punch, sweetened juice, sweetened or flavored water, Gatorade, or sweet tea) but excluding 100% juice): categorical (Infant Diet Quality Index component score from 0–1 based on degree of adherence to guidelines; max score: introduced at ≥12 mo); [underlined: Dietary assessment methods:] 24-h dietary recall via telephone interview with caregiver; [underlined: Age(s) at dietary assessment:] 1, 3, 5, 7, 9 11, 13, 15, 18, 24, 30, 36, 42, and 48 mo; [underlined: Age of introduction:] ≥12 mo: 34.0%; [underlined: Outcome(s):] BMIZ; [underlined: Outcome assessment methods:] Weight and length/height collected at WIC sites or from child's health care provider. BMIZ based on CDC age- and sex-specific growth charts; [underlined: Age(s) at outcome assessment:] 2, 3, 4 y | [underlined: BMIZ @ 2, 3, 4 y]; 2 y: Data NR, p>0.10; 3 y: Data NR, p>0.10; 4 y: greater adherence associated with lower BMIZ, p<0.05 | [underlined: Key confounders accounted for:] SEP; sex; gestational age; [underlined: Key confounders NOT accounted for:] race and/or ethnicity; milk feeding practices; baseline anthropometry; [underlined: Model adjustments:] None; [underlined: Funding:] NHLBI; USDA/NIFA
Becker, 2023 (https://pubmed.ncbi.nlm.nih.gov/36629571/)^21^; PCS, IVAPSA, Brazil; [underlined: Analytic N] = 103 (Excluded participants with missing data on exposure and/or outcome.); [underlined: Adequately powered:] No; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race and/or ethnicity:] Maternal race/skin color: White: 58.3%, Black: 23.3%, Other (yellow and brown): 18.4%; [underlined: Maternal education:] Maternal education level (y): 0–8: 29.1%, 9–11: 57.3%, >11: 13.6%; [underlined: Other SEP measure(s):] Family income (reais, Median (25th, 75th percentile)): 1,950 (1,200, 3,000); [underlined: Maternal age:] Median (25th, 75th percentile): 28 (21, 33) y; [underlined: Milk feeding practices:] Ever BF: 77.7%; [underlined: Child sex (female):] 59%; [underlined: Birth size:] NR; [underlined: Gestational age:] NR | [underlined: Exposure(s) and comparator(s):] Age of introduction to fruit juice (including natural fruit juice, concentrated fruit juice, diluted fruit juice, and artificial fruit juices - powdered juices, nectars, and fruit drinks): <6 mo vs ≥6 mo; [underlined: Dietary assessment methods:] Maternal questionnaire; [underlined: Age(s) at dietary assessment:] 6 mo; [underlined: Age of introduction:] <6 mo: 72.8%, ≥6 mo: 27.2%; [underlined: Outcome(s):] BMIZ, Risk of overweight; [underlined: Outcome assessment methods:] Weight and height measured by research staff. BMIZ calculated based on WHO growth curves.; [underlined: Age(s) at outcome assessment:] Preschool age (3–6 y) | [underlined: BMIZ @ 3–6 y (Mean)]; Juice <6 mo vs ≥6 mo; 0.88 vs 0.55, p=0.282; [underlined: Change in BMIZ from 6 mo to 3–6 y (Mean)]; Juice <6 mo vs ≥6 mo; 0.5 vs 0.4, p=0.824; [underlined: Weight status @ 3–6 y (%)]; Juice <6 mo vs ≥6 mo Thinness: 5.3% vs 3.6%; Normal weight and risk of overweight: 66.7% vs 75.0%; Overweight/obese: 28.0% vs 21.4% p=0.843 | [underlined: Key confounders accounted for:] SEP; sex; race and/or ethnicity; milk feeding practices; baseline anthropometry; [underlined: Key confounders NOT accounted for:] gestational age; [underlined: Model adjustments:] None; [underlined: Funding:] PAPERGS/CNPq; FIPE/HCPA; PRONEX 2009
Cantoral, 2016 (https://pubmed.ncbi.nlm.nih.gov/25891908/)^22^; PCS, ELEMENT, Mexico; [underlined: Analytic N] = 227 (Excluded participants who did not enroll in follow-up study and who were not selected for new study centre, or had incomplete data for relevant variables (socio-demographic, dietetic, anthropometric, and physical activity variables)); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race and/or ethnicity:] NR; [underlined: Maternal education:] NR; [underlined: Other SEP measure(s):] SES level (pesos/mo): E ($0–2,699): 8%, D ($2,700–6,799): 20%, D+ ($6,800–11,599): 51.3%, C ($11,600–34,999): 19.3%, C+ ($35,000–84,999): 1.4%, A/B (>$85,000): 0%; [underlined: Maternal age:] NR; [underlined: Milk feeding practices:] Partial BF until 12 mo: 31%; [underlined: Child sex (female):] 54%; [underlined: Birth size:] NR; [underlined: Gestational age:] NR | [underlined: Exposure(s) and comparator(s):] Age of introduction to SSB (sodas, commercial fruit drinks, flavored water with sugar; does not include natural fruit or vegetable juice): ≤12 mo vs >12 mo (ref); [underlined: Dietary assessment methods:] Semi-quantitative FFQ (child diet previous 3 mo) administered by trained personnel to mother; [underlined: Age(s) at dietary assessment:] 12 mo; [underlined: Age of introduction:] ≤12 mo: 73%, >12 mo: 27%; [underlined: Outcome(s):] Obesity, Abdominal obesity; [underlined: Outcome assessment methods:] Weight, height, and WC measured by trained personnel. Obesity classified using WHO criteria (>2 SD of the z-score for BMI).; Abdominal obesity defined as waist circumference ≥90th percentile for age and sex; [underlined: Age(s) at outcome assessment:] 8–14 y (8–9y: 47%, 10–11y: 31%, 12–14y: 22%) | [underlined: Abdominal obesity @ 8–14 y (OR (95% CI))]; 1.70 (0.70, 4.09); [underlined: Obesity @ 8–14 y (OR (95% CI))]; 2.00 (0.87, 4.59) | [underlined: Key confounders accounted for:] SEP; sex; milk feeding practices; baseline anthropometry; [underlined: Key confounders NOT accounted for:] race and/or ethnicity; gestational age; [underlined: Model adjustments:] sex, any BF up to age 12 mo, maternal obesity at 12 mo postpartum, concurrent age, non-SSB energy intake, physical activity, TV watching; [underlined: Funding:] NIEHS; Consejo Nacional de Ciencia y Tecnologia; NIEHS/US EPA Formative Children's Center for Environmental Health and Disease Prevention Research
Carruth, 2000 (https://pubmed.ncbi.nlm.nih.gov/10872903/)^3^; PCS, U.S.; [underlined: Analytic N] = 94 (Reasons for attrition NR); [underlined: Adequately powered:] Yes; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race and/or ethnicity:] White: 100%; [underlined: Maternal education:] College degree: 50%; [underlined: Other SEP measure(s):] Hollingshead Index: 54 (9) - all "middle or upper SES families"; [underlined: Maternal age:] 31 y; [underlined: Milk feeding practices:] Ever BF: 83%, EBF at 4 mo: 33%, Mixed feeding at 4 mo: 33%, EBF at 6 mo: 12%; [underlined: Child sex (female):] 46%; [underlined: Birth weight:] Males: 7.8 (1.2) lb, Females: 7.6 (1.1) lb; [underlined: Gestational age:] 100% full-term | [underlined: Exposure(s) and comparator(s):] Age introduced to juice (not defined): Continuous; [underlined: Dietary assessment methods:] 24-h recall (maternal report) with dietitian; [underlined: Age(s) at dietary assessment:] 2, 3, 4, 6, 8, 10, 12, 16, 20, 24 mo (interviewed 3–5x from 2–10 mo, 2–4x from 12–24 mo); [underlined: Age of introduction:] Median (range): 4.5 (1–11) mo; [underlined: Outcome(s):] Weight, length, Change in weight slope relative to length slope; [underlined: Outcome assessment methods:] Weight and length measured by research staff; [underlined: Age(s) at outcome assessment:] 2, 3, 4, 6, 8, 10, 12, 16, 20, 24 mo (measured 3–5x from 2–10 mo, 2–4x from 12–24 mo) | [underlined: Change in weight @ 2–8 mo, 12–24 mo (β (SE))]; Change from 2–8 mo: Data NR, p>0.05; Change from 12–24 mo: Data NR, p>0.05; [underlined: Change in length @ 2–8 mo, 12–24 mo (β (SE))]; Change from 2–8 mo: Data NR, p>0.05; Change from 12–24 mo: Data NR, p>0.05; [underlined: Change in weight slope relative to length slope @ 2–8 mo, 12–24 mo (β (SE))]; Change from 2–8 mo: Data NR, p>0.05; Change from 12–24 mo: Data NR, p>0.05 | [underlined: Key confounders accounted for:] SEP; sex; race and/or ethnicity; milk feeding practices; gestational age; baseline anthropometry; [underlined: Key confounders NOT accounted for:] None; [underlined: Model adjustments:] NA (variable not retained in model); [underlined: Funding:] NR
Gingras, 2019 (https://pubmed.ncbi.nlm.nih.gov/31757860/)^4^; PCS, Project Viva, U.S.; [underlined: Analytic N] = 1,013 (Excluded participants who did not have complete exposure data, did not have outcomes measured, and children born <34 wk gestation); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race and/or ethnicity:] NR (Child race and/or ethnicity: White: 69%, Black or African American: 12%, Other: 12%, Hispanic: 4%, Asian: 3%); [underlined: Maternal education:] College graduate: 74%; [underlined: Other SEP measure(s):] Household income >$70,000/y: 66%; [underlined: Maternal age:] 32.6 (4.8) y; [underlined: Milk feeding practices:] Any BF at 4 mo: 69%; [underlined: Child sex (female):] 51%; [underlined: Birth weight:] 3.53 (0.52) kg; [underlined: Birth weight for gestational age z score:] 0.23 (0.97); [underlined: Gestational age:] 39.7 (1.4) wk | [underlined: Exposure(s) and comparator(s):] Timing of introduction to fruit juice (not defined): <4 mo, 4-<6 mo (ref), ≥6 mo; [underlined: Dietary assessment methods:] Maternal questionnaire; [underlined: Age(s) at dietary assessment:] 6, 12 mo; [underlined: Age of introduction:] <4 mo: 5.6%, 4-<6 mo: 23.7%, ≥6 mo: 70.8%; [underlined: Outcome(s):] BMIZ, WC, DXA whole-body fat percentage, DXA truncal fat mass, sum of skinfolds (subscapular plus triceps), skinfold ratio (subscapular/triceps); [underlined: Outcome assessment methods:] All outcomes measured by trained research staff. Age- and sex-specific BMIZ calculated using U.S. national reference data. Whole-body fat percentage and truncal fat mass measured via DXA.; [underlined: Age(s) at outcome assessment:] Mean (SD): 7.9 (0.8) y; 13.2 (0.9) y | [underlined: BMIZ @ ~8 y (β (95% CI))]; Among infants BF ≥4 mo:; <4 mo vs 4-<6 mo (ref): 0.46 (0.04, 0.88); ≥6 mo vs 4-<6 mo (ref): 0.03 (−0.14, 0.21); Among infants FF (never BF or stopped BF by 4 mo):; <4 mo vs 4-<6 mo (ref): 0.12 (−0.30, 0.53); ≥6 mo vs 4-<6 mo (ref): −0.10 (−0.37, 0.16); [underlined: BMIZ @ ~13 y (β (95% CI))]; Among infants BF ≥4 mo:; <4 mo vs 4-<6 mo (ref): 0.21 (−0.24, 0.67); ≥6 mo vs 4-<6 mo (ref): 0.03 (−0.16, 0.22); Among infants FF (never BF or stopped BF by 4 mo):; <4 mo vs 4-<6 mo (ref): 0.34 (−0.11, 0.79); ≥6 mo vs 4-<6 mo (ref): −0.04 (−0.35, 0.26); [underlined: WC (cm) @ ~8 y (β (95% CI))]; Among infants BF ≥4 mo:; <4 mo vs 4-<6 mo (ref): 3.44 (0.48, 6.40); ≥6 mo vs 4-<6 mo (ref): 0.10 (−1.14, 1.35); Among infants FF (never BF or stopped BF by 4 mo):; <4 mo vs 4-<6 mo (ref): 1.33 (−2.16, 4.82); ≥6 mo vs 4-<6 mo (ref): −1.01 (−3.24, 1.23); [underlined: WC (cm) @ ~13 y (β (95% CI))]; Among infants BF ≥4 mo:; <4 mo vs 4-<6 mo (ref): 2.71 (−1.93, 7.35); ≥6 mo vs 4-<6 mo (ref): −0.00 (−1.96, 1.96); Among infants FF (never BF or stopped BF by 4 mo):; <4 mo vs 4-<6 mo (ref): 3.63 (−1.73, 8.99); ≥6 mo vs 4-<6 mo (ref): −2.43 (−6.05, 1.18) | [underlined: Key confounders accounted for:] SEP; sex; race and/or ethnicity; milk feeding practices; gestational age; baseline anthropometry; [underlined: Key confounders NOT accounted for:] None; [underlined: Model adjustments:] child sex, child age, maternal education level, marital status, household income, maternal prepregnancy BMI, paternal BMI, child's race and/or ethnicity, gestational age at delivery, change in WAZ from 0 to 4 mo.; [underlined: Funding:] NIH, CIHR
Pan, 2014 (https://pubmed.ncbi.nlm.nih.gov/25183752/)^23^; PCS, IFPS II, U.S.; [underlined: Analytic N] = 1,189 (Excluded participants tha were lost to follow-up, were >13 mo at IFPS survey, did not have anthropometric measurements at 6 y, had height, weight, or BMI at follow-up that was biologically implausible, or did not have data on SSBs.); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race and/or ethnicity:] White, non-Hispanic: 88.0%, Hispanic: 4.8%, Other, non-Hispanic 3.9%, Black, non-Hispanic: 3.4%; [underlined: Maternal education:] HS or less: 16.1%, Some college: 34.8%, College graduate: 49.0%; [underlined: Other SEP measure(s):] Income-to-poverty ratio: <185%: 33.6%, 185%-349%: 37.9%, ≥350%: 28.5%; [underlined: Maternal age:] 18–24 y: 13.5%, 25–29 y: 33.2%, 30–34 y: 32.3%, ≥20.9%; [underlined: Milk feeding practices:] BF <6 mo: 48.6%, BF ≥6 mo: 51.4%; [underlined: Child sex (female):] 50%; [underlined: Birth weight:] ≤4,000 g: 87.1%, >4,000 g: 12.9%; [underlined: Gestational age:] NR | [underlined: Exposure(s) and comparator(s):] Age at introduction to SSBs (juice drinks, soft t drinks, soda, sweet tea, Kool-Aid [Kraft II foods, West Plains, NY]): Never during infancy (ref), ≥6 mo, <6 mo, Any during infancy (≥6 mo and <6 mo combined); [underlined: Dietary assessment methods:] Maternal questionnaire; [underlined: Age(s) at dietary assessment:] 1, 2, 3, 4, 5, 6, 7, 8, 9, 10, 12 mo; [underlined: Age of introduction:] Never during infancy: 74.1%, ≥6 mo: 18.8%, <6 mo: 8.5%; [underlined: Outcome(s):] Obesity; [underlined: Outcome assessment methods:] Height and weight measured and reported by mothers; given instructions in questionnaire on how to complete measurements. Obesity defined as sex-specific BMI-for-age ≥95th percentile according to 2000 CDC growth charts; [underlined: Age(s) at outcome assessment:] 6 y | [underlined: Obesity @ 6 y (OR (95% CI))]; Age of SSB introduction; Any during infancy vs none (ref): 1.71 (1.09, 2.68); ≥6 mo vs never (ref): 1.61 (0.96, 2.71); <6 mo vs never (ref): 1.92 (1.01, 3.66) | [underlined: Key confounders accounted for:] SEP; sex; race and/or ethnicity; milk feeding practices; [underlined: Key confounders NOT accounted for:] gestational age; baseline anthropometry; [underlined: Model adjustments:] Sex, birth weight, age at solid food introduction, BF duration, maternal age, maternal race/ethnicity, maternal education, marital status, income-to-poverty ratio, prepregnancy weight status; [underlined: Funding:] FDA; CDC; Office of Women's Health; NIH; Maternal and Child Health Bureau
Robinson, 2022 (https://pubmed.ncbi.nlm.nih.gov/35182582/)^24^; PCS, Upstate KIDS, U.S.; [underlined: Analytic N] = 1,713–2,056 (at 2–3 y), 1,283–1,373 (at 7–9 y) (Excluded participants without data on the exposure or outcome, and 1 randomly selected twin from twin pairs.); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race and/or ethnicity:] Non-Hispanic White: ~86%; [underlined: Maternal education:] Less than high school: ~2%, HS or GED equivalent: ~7%, Some college: ~23%, College: ~27%, Advanced degree: ~40%; [underlined: Other SEP measure(s):] Household income: $10,000–24,999: ~8%, $25,000–49,999: ~14%, $50,000–74,999: ~21%, $75,000-99,999: ~22%, ≥$100,000" ~35%; WIC participation: ~15%; Private insurance: ~87%; [underlined: Maternal age:] ~31 y; [underlined: Milk feeding practices:] BF at 4 mo: ~59%; [underlined: Child sex (female):] ~48%; [underlined: Birth size:] NR; [underlined: Gestational age:] NR | [underlined: Exposure(s) and comparator(s):] Timing of juice introduction (does not distinguish between 100% juice vs juice drinks [e.g., juice with added water, artificial sweeteners, or sugar]): <6 mo, 6-<12 mo, ≥12 mo (ref); <6 mo, 6-<9 mo, 9-<12 mo, ≥12 mo (ref); [underlined: Dietary assessment methods:] Maternal questionnaire; [underlined: Age(s) at dietary assessment:] 4, 8, 12, 18 mo; [underlined: Age of introduction:] <6 mo: ~15%, 6-<12 mo: ~49%, ≥12 mo: ~33%; [underlined: Outcome(s):] BMIZ, WAZ, HAZ, overweight/obesity; obesity; [underlined: Outcome assessment methods:] Height/length and weight measured via maternal report. Age- and sex-standardized WAZ, HAZ, and BMIZ calculated using CDC reference. Overweight/obesity defined as ever having BMIZ ≥85th %ile during age range. Obesity defined as ever having BMIZ ≥95th %ile during age range.; [underlined: Age(s) at outcome assessment:] 2–3 y, 7–9 y | [underlined: WAZ @ 2–3 y and 7–9 y (Mean difference (95% CI))]; 2–3 y; <6 mo vs ≥12 mo (ref): 0.21 (0.04, 0.37); 6-<12 mo vs ≥12 mo (ref): −0.03 (−0.14, 0.08); p-trend: 0.02; 7–9 y; <6 mo vs ≥12 mo (ref): 0.27 (0.06, 0.49); 6-<12 mo vs ≥12 mo (ref): −0.01 (−0.14, 0.15); p-trend: 0.02; [underlined: HAZ @ 2–3 y and 7–9 y (Mean difference (95% CI))]; 2–3 y; <6 mo vs ≥12 mo (ref): 0.32 (−0.14, 0.79); 6-<12 mo vs ≥12 mo (ref): 0.03 (−0.33, 0.39); p-trend: 0.32; 7–9 y; <6 mo vs ≥12 mo (ref): −0.02 (−0.27, 0.22); 6-<12 mo vs ≥12 mo (ref): 0.05 (−0.11, 0.22); p-trend: 0.91; [underlined: BMIZ @ 2–3 y and 7–9 y (Mean difference (95% CI))]; 2–3 y; <6 mo vs ≥12 mo (ref): −0.23 (−0.45, 0.35); 6-<12 mo vs ≥12 mo (ref): −0.16 (−0.45, 0.07); p-trend: 0.40; 7–9 y; <6 mo vs ≥12 mo (ref): 0.38 (0.12, 0.64); 6-<12 mo vs ≥12 mo (ref): −0.02 (−0.19, 0.15); p-trend: 0.01; [underlined: Overweight/obesity @ 2–3 y and 7–9 y (RR (95% CI))]; 2–3 y; <6 mo vs ≥12 mo (ref): 1.09 (0.73, 1.63); 6-<12 mo vs ≥12 mo (ref): 0.84 (0.62, 1.15); p-trend: 0.53; 7–9 y; <6 mo vs ≥12 mo (ref): 1.54 (0.99, 2.38); 6-<12 mo vs ≥12 mo (ref): 0.94 (0.65, 1.37); p-trend: 0.005; [underlined: Obesity @ 2–3 y and 7–9 y (RR (95% CI))]; 2–3 y; <6 mo vs ≥12 mo: 1.16 (0.62, 2.16); 6-<12 mo vs ≥12 mo: 1.11 (0.69, 1.78); p-trend: 0.29; 7–9 y; <6 mo vs ≥12 mo: 2.17 (1.11, 4.23); 6-<12 mo vs ≥12 mo: 1.10 (0.62, 1.95); p-trend: 0.001; Examining data with the 6-<12 mo group broken into 6-<9 mo and 9-<12 mo did not change results. | [underlined: Key confounders accounted for:] SEP; sex; race and/or ethnicity; milk feeding practices; [underlined: Key confounders NOT accounted for:] gestational age; baseline anthropometry; [underlined: Model adjustments:] Child age at time of assessment, maternal age at baseline, pre-pregnancy BMI, race/ethnicity, education, WIC participation, fertility treatment use, smoking during pregnancy, gestational hypertension, residence type, household income, paternal BMI, child's sex, twin status, age at solid food introduction (midpoint), and any breastfeeding at 4 mo; [underlined: Funding:] NICHD
Santorelli, 2014 (https://pubmed.ncbi.nlm.nih.gov/24513174/)^25^; PCS, Born in Bradford, U.K.; [underlined: Analytic N] = 743 (Excluded participants without information on infant feeding, had missing obstetric or covariate data, were from multiple births, or were not of White British or Pakistani ethnicity.); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race and/or ethnicity:] Pakistani: 49%, White British: 38%, Other South Asian: 7%, Other: 6% (Note - Other South Asian and Other were excluded from analyses); [underlined: Maternal education:] <5 GCSE equivalent: ~22%, ≥5 GCSE equivalent: ~33%, A-level equivalent: ~25%, > A-level equivalent: 25%, Foreign unknown/other: ~6%; [underlined: Other SEP measure(s):] NR; [underlined: Maternal age:] ~27 y; [underlined: Milk feeding practices:] Replaced BM with formula milk before introducing solid foods: ~39%; Continued BF after introducing solid foods: ~32%; [underlined: Child sex (female):] NR; [underlined: Low birth weight (<2,500 g):] ~8%; [underlined: Gestational age:] Preterm (<37 wk): ~5% | [underlined: Exposure(s) and comparator(s):] Introduction to sweetened drinks (e.g., cola, squash, lemonade, sweetened tea, pre-pared "baby" drinks): <17 wk vs ≥17 wk (ref); [underlined: Dietary assessment methods:] Maternal questionnaire; [underlined: Age(s) at dietary assessment:] 6 mo, 12 mo; [underlined: Age of introduction:] Sweetened drinks <17 wk: ~10%; [underlined: Outcome(s):] BMIZ; [underlined: Outcome assessment methods:] Weight and height measured. BMI converted into age- and sex-adjusted BMIZ according to WHO 2006 growth standards.; [underlined: Age(s) at outcome assessment:] 3 y; [underlined: Outcome(s):] BMIZ; [underlined: Outcome assessment methods:] Weight and height measured. BMI converted into age- and sex-adjusted BMIZ according to WHO 2006 growth standards.; [underlined: Age(s) at outcome assessment:] 3 y | [underlined: BMIZ @ 3 y (mean difference (95% CI))]; <17 wk vs >17 wk (ref): −0.10 (−0.36, 0.16) | [underlined: Key confounders accounted for:] SEP; sex; race and/or ethnicity; milk feeding practices; gestational age; [underlined: Key confounders NOT accounted for:] baseline anthropometry; [underlined: Model adjustments:] Ethnicity, maternal age, educational level, marital status, maternal smoking during pregnancy, maternal BMI, parity, preterm birth, low birth weight, mode of delivery, duration of BF, all other infant feeding practices (early introduction to solid foods, sweetened foods given as a first food, sweetened drinks given at <17 wk of age, replaced BM with formula milk before introducing solid foods, continuing BF after introducing solid foods); [underlined: Funding:] NIHR
Woo, 2013 (https://pubmed.ncbi.nlm.nih.gov/23236024/)^8^; PCS, GEHM, China, Mexico, U.S.; [underlined: Analytic N] = 285 (Excluded participants who were lost to follow-up); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race and/or ethnicity:] NR (Country: China: ~36%, Mexico: ~31%, U.S.: ~32%); [underlined: Maternal education:] China, Mexico, U.S., respectively: ≤HS graduate: 18.3%, 93.2%, 5.0%, Attended or graduated from college: 72.5%, 5.9%, 78.3%, Post-college education: 9.2%, 0.8%, 16.7%; [underlined: Other SEP measure(s):] Employed at time of pregnancy: 71.4% (China), 40.7% (Mexico), 80.8% (U.S.); WIC (U.S.): ~34%, Nutrisano supplemental food program (Mexico): 0%, Supplemental food programs in Shanghai (China): 0%; [underlined: Maternal age:] 29.3 (3.7) y (China), 24.4 (5.6) y (Mexico), 31.5 (5.2) y (U.S.); [underlined: Milk feeding practices:] EBF duration (median (IQR)): China: 4.9 (1.6, 11.9) wk, Mexico: 7.1 (0.0, 18.0) wk, U.S.: 13.7 (4.6, 19.3) wk. BF duration (median): China: 37.1 wk, Mexico: 52.0 wk, U.S.: 49.5 wk; [underlined: Child sex (female):] 49%; [underlined: Birth weight:] ~3.4 kg; [underlined: Gestational age:] 100% ≥37 wk gestation | [underlined: Exposure(s) and comparator(s):] Timing of introduction to fruit/vegetable juice (not defined as 100%), soft drinks: Continuous (fruit/vegetable juice), Ever vs never introduced in the first year (soft drinks); [underlined: Dietary assessment methods:] Maternal 24 h food frequency recall via telephone.; [underlined: Age(s) at dietary assessment:] 2–52 wk, weekly; [underlined: Age of introduction:] Median (IQR) for China, Mexico, and U.S., respectively (mo): Juice (fruit or vegetable): 4.3 (3.5, 5.3), 6.8 (6.2, 7.6), 9.1 (7.1, 10.4); Soft drinks: 0, 9.6 (8.8, 11.1), 11.1 (10.1, 12.0); [underlined: Outcome(s):] WAZ, LAZ, BMIZ; [underlined: Outcome assessment methods:] Weight and length measured by trained study personnel. WAZ, LAZ, and BMIZ calculated using age- and sex-specific z-scores from the 2005 WHO infant growth standards.; [underlined: Age(s) at outcome assessment:] 1 y | [underlined: WAZ @ 1 y]; Fruit/vegetable juice: Data NR, p≥0.20 Soft drinks: Data NR, p≥0.20; [underlined: LAZ @ 1 y]; Fruit/vegetable juice: Data NR, p≥0.20 Soft drinks: Data NR, p≥0.20; [underlined: BMIZ @ 1 y]; Fruit/vegetable juice: Data NR, p≥0.20 Soft drinks: Data NR, p≥0.20 | [underlined: Key confounders accounted for:] SEP; sex; milk feeding practices; gestational age; [underlined: Key confounders NOT accounted for:] race and/or ethnicity; baseline anthropometry; [underlined: Model adjustments:] Cohort site; [underlined: Funding:] Mead Johnson Nutrition Inc; NIH/NICHD; NIH/NCRR (Institutional Clinical and Translational Science Award)

a Abbreviations: @: at; β: beta; BF: breastfeeding; BM: breast milk; BMI: body mass index; BMIZ: BMI z-score; CDC: Centers for Disease Control and Prevention; CI: confidence interval; cm: centimeter; DXA: dual-energy X-ray absorptiometry; EBF: exclusive breastfeeding; ELEMENT: Early Life Exposure in Mexico to Environmental Toxicants; FF: formula feeding; FFQ: food frequency questionnaire; g: gram; GCSE: General Certificate of Secondary Education; GED: General Educational Development; GEHM: Global Exploration of Human Milk; h: hour; HAZ: height-for-age z-score; HS: high school; IFPS II: Infant Feeding Practices Study II; IQR: interquartile range; IVAPSA: Impact of Perinatal Environmental Variations in the First 6 Months of Life; kg: kilogram; LAZ: length-for-age z-score; lb: pound; mo: month; NR: not reported; OR: odds ratio; PCS: prospective cohort study; ref: reference; RR: risk ratio; SD: standard deviation; SE: standard error; SEP: socioeconomic position; SES: socioeconomic status; SSB: sugar-sweetened beverage; U.K.: United Kingdom; U.S.: United States; WAZ: weight-for-age z-score; WC: waist circumference; WHO: World Health Organization; WIC: Special Supplemental Nutrition Program for Women, Infants, and Children; WIC ITFPS-2: WIC Infant and Toddler Feeding Practices Study-2; wk: week; x: times; y: year

Table 25 Risk of bias for observational studies examining timing of introduction to sugar-sweetened beverages and growth, body composition, and risk of obesity ^a^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Au, 2023^6^ | HIGH | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Becker, 2023^21^ | SOME CONCERNS | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Cantoral, 2016^22^ | SOME CONCERNS | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Carruth, 2000^3^ | LOW | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Gingras, 2019^4^ | LOW | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Pan, 2014^23^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | HIGH
Robinson, 2022^24^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | HIGH
Santorelli, 2014^25^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Woo, 2013^8^ | VERY HIGH | SOME CONCERNS | LOW | LOW | LOW | LOW | HIGH | VERY HIGH

a Possible ratings of low, some concerns, high, very high, no information, or not applicable determined using the "Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)" tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602. ) *Low risk of bias except for concerns about uncontrolled confounding.

### Food sources of added sugars

#### Description of the evidence

One PCS met inclusion criteria and examined the relationship between the timing of introduction of food sources of added sugars among infants and young children, up to age 24 months, and growth, body composition, or risk of obesity (Table 27).^25^

##### Population

The study was conducted in the United Kingdom as part of the Born in Bradford cohort. The analytic sample size was 743 and the study did not report power. Forty-nine percent of the participants were Pakistani and 38% were White British, while the remaining participants were reported as Other South Asian (7%) and Other (6%). Only participants who were Pakistani or White British were included in the analyses. The average age of the mothers were about 27 years. Regarding SEP, the study reported a range of educational levels across the mothers: approximately 22% had the equivalent of less than 5 General Certificate of Secondary Education, approximately 33% had at least 5 General Certificate of Secondary Education, approximately 25% had an A-level equivalent, and approximately 25% had greater than an A-level equivalent. About 39% replaced breast milk with formula milk before introducing solid foods and 32% continued to breastfeed after introducing solid foods. Only 8% of the infants had low birth weight and 5% were born preterm. Growth, body composition, or risk of obesity at baseline was not reported.

##### Exposure and comparator

This study assessed introduction of sweetened foods (e.g., egg custard, rice pudding, sweetened rusks, biscuits, cakes) as a first food dichotomously (yes versus no). The exposure variable was assessed using a maternal questionnaire at ages 6 and 12 months.

##### Outcome

This study examined BMIZ at age 3 years, which was measured by research personnel. Age- and sex-adjusted BMIZ were based on WHO growth standards.

#### Synthesis of the evidence

The single study that met inclusion criteria and assessed timing of food sources of added sugars reported that sweetened foods introduced as a first food was not associated with BMIZ at age 3 years, but trended towards greater BMIZ (Table 27).^25^

#### Conclusion statement and grade

The Committee did not draw a conclusion statement about the relationship between the timing of introduction of food sources of added sugars in infants and young children, up to age 24 months, and growth, body composition, and risk of obesity because there is not enough evidence (Table 26). Publication bias may be a limitation, but the small body of evidence makes it difficult to assess. However, while the literature search was comprehensive, a search of the gray literature was not done, which could increase the possibility of publication bias. The risk of bias for the study that addressed this question is documented in Table 28.

Table 26 Conclusion statement, grade for timing of introduction of food sources of added sugars and growth, body composition, and risk of obesity

Conclusion Statement | A conclusion statement cannot be drawn about the relationship between the age when infants and young children, up to age 24 months, are introduced to food sources of added sugars and outcomes related to growth patterns, body composition, and risk of obesity during childhood because there is not enough evidence available.
Grade | Grade Not Assignable
Body of Evidence | 1 article: 1 prospective cohort study.
Rationale | There was not enough evidence to synthesize this body of evidence.

Table 27 Evidence examining the relationship between timing of introduction to food sources of added sugars and growth, body composition, and risk of obesity ^a^

Study and Participant Characteristics | Exposure, Comparator, Outcome | Results | Key Confounders, Model Adjustments, Funding
Santorelli, 2014 (https://pubmed.ncbi.nlm.nih.gov/24513174/)^25^; PCS, Born in Bradford, U.K.; [underlined: Analytic N] = 743 (Excluded participants without information on infant feeding, had missing obstetric or covariate data, were from multiple births, or were not of White British or Pakistani ethnicity.); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race and/or ethnicity:] Pakistani: 49%, White British: 38%, Other South Asian: 7%, Other: 6% (Note - Other South Asian and Other were excluded from analyses); [underlined: Maternal education:] <5 GCSE equivalent: ~22% GCSE equivalent: ~33%, A-level equivalent: ~25%, > A-level equivalent: 25%, Foreign unknown/other: ~6%; [underlined: Other SEP measure(s):] NR; [underlined: Maternal age:] ~27 y; [underlined: Milk feeding practices:] Replaced BM with formula milk before introducing solid foods: ~39%; Continued BF after introducing solid foods: ~32%; [underlined: Child sex (female):] NR; [underlined: Low birth weight (<2,500 g):] ~8%; [underlined: Gestational age:] Preterm (<37 wk): ~5% | [underlined: Exposure(s) and comparator(s):] Sweetened foods (e.g., egg custard, rice pudding, sweetened rusks, biscuits, cake): Introduced as a first food vs Not (ref)); [underlined: Dietary assessment methods:] Maternal questionnaire; [underlined: Age(s) at dietary assessment:] 6 mo, 12 mo; [underlined: Age of introduction:] Sweetened foods introduced as a first food: ~50% ≥5; [underlined: Outcome(s):] BMIZ; [underlined: Outcome assessment methods:] Weight and height measured. BMI converted into age- and sex-adjusted BMIZ according to WHO 2006 growth standards.; [underlined: Age(s) at outcome assessment:] 3 y | [underlined: BMIZ @ 3 y (mean difference (95% CI))] Sweetened foods given as first food vs not (ref): 0.03 (−0.12, 0.19) | [underlined: Key confounders accounted for:] SEP; sex; race and/or ethnicity; milk feeding practices; gestational age; [underlined: Key confounders NOT accounted for:] baseline anthropometry; [underlined: Model adjustments:] Ethnicity, maternal age, educational level, marital status, maternal smoking during pregnancy, maternal BMI, parity, preterm birth, low birth weight, mode of delivery, duration of BF, all other infant feeding practices (early introduction to solid foods, sweetened foods given as a first food, sweetened drinks given at <17 wk of age, replaced BM with formula milk before introducing solid foods, continuing BF after introducing solid foods); [underlined: Funding:] NIHR

a Abbreviations: @: at; BF: breastfeeding; BM: breast milk; BMI: body mass index; BMIZ: BMI z-score; CI: confidence interval; GCSE: General Certificate of Secondary Education; g: gram; mo: month; NR: not reported; PCS: prospective cohort study; ref: reference; SEP: socioeconomic position; U.K.: United Kingdom; WHO: World Health Organization; wk: week; y: year

Table 28 Risk of bias for observational studies examining timing of introduction to food sources of added sugars and growth, body composition, and risk of obesity ^a^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Santorelli, 2014^25^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH

a Possible ratings of low, some concerns, high, very high, no information, or not applicable determined using the "Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)" tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602. ) *Low risk of bias except for concerns about uncontrolled confounding.

## Types and amounts of complementary foods and beverages

### 100% juice

#### Description of the evidence

Four studies (4 articles) met inclusion criteria and examined the relationship between 100% juice consumption by infants and young children, up to 24 months, and growth, body composition, and risk of obesity (Table 30).^1,26–28^ All 4 studies were PCS, using data from the following cohorts: IFPS II,^26^ Born in Bradford 1000,^27^ Study of Women, Infant Feeding, and Type 2 Diabetes after Gestational Diabetes Mellitus pregnancy,^28^ and 1 unnamed cohort.^1^

##### Population

The studies were conducted in the United States^1,26,28^ (including 1 study conducted in Puerto Rico)^1^ and the United Kingdom.^27^ The analytic sample sizes of the studies ranged from 681 to 835.^28^ None of the studies reported power calculations related to 100% juice consumption and the relevant outcomes.

All studies provided information on the racial and/or ethnic background of participants. This varied across the studies: 100% Hispanic in 1 study,^1^ approximately 95% White, 4% Hispanic, and 2% Black in another,^26^ approximately 56% Pakistani and 44% White British in the third,^27^ and 37% non-Hispanic Asian, 30% Hispanic, 23% non-Hispanic White, 8% non-Hispanic Black, and 2% “mixed race/other” in the final study.^28^ Across the 3 studies that reported maternal age, the women tended to be in their mid-twenties and early thirties.^1,26,28^ Human milk and formula feeding practices were reported in 3 studies and tended to vary: 1 study reported an average duration of breastfeeding of 9 months,^28^ a second reported that 21% of participants were breastfeeding at 10 months,^1^ and the third reported that 52% of mothers had low breastfeeding intensity from 6–12 months.^26^ SEP was reported for 3 studies.^1,26,28^ Maternal education was reported across all 3 of these studies, showing that participants tended to have greater than a high school education level.^1,26,28^ WIC participation was reported in 2 studies: 1 study exclusively enrolled individuals participating in WIC,^1^ while the other reported that 25% of the women participated in WIC.^28^ Finally, 1 study assessed income in relationship to the FPL, reporting that approximately 25% of participants had an income less than 185% of the FPL while about 44% of participants had an income greater than 349% of the FPL.^26^ One study was conducted exclusively with women who had gestational diabetes.

Regarding the characteristics of the infants and young children, the studies noted that approximately 50% of participants were female (3 studies),^1,26,28^ mean birth weight ranged from approximately 3.2 to 3.5 kg (3 studies),^26–28^ and gestational age was approximately 39 weeks in 1 study^28^ and greater than 35 weeks for all participants in a second study.^26^ Growth, body composition, and risk of obesity at baseline were not reported.

##### Exposures and comparators

The studies used a variety of assessment methods to measure 100% juice consumption. Two studies used a FFQ,^1,27^ while the remaining 2 studies used a survey or questionnaire other than an FFQ.^26,28^ Regarding how the exposures were analyzed, 2 studies examined frequency of consumption, 2 studies compared consumers to non-consumers, and 1 study examined changes in the Diet Quality Index Score component score for 100% fruit juice which was based on amounts consumed per day. All of the studies assessed 100% juice consumption multiple times from birth up to age 24 months, all of which included assessments up to age 12 months^1,26–28^ and 2 included assessments beyond age 12 months.^1,27^

##### Outcomes

Each study assessed a unique outcome measure related to growth or risk of overweight or obesity; none of the studies assessed a measure of body composition. Specifically, the 4 studies analyzed: WAZ,^26^ BMIZ,^27^ odds of WLZ ≥1 at follow-up,^1^ and the risk of overweight and risk of obesity based on BMIZ percentiles.^28^ All studies used CDC^26,28^ or WHO growth standards^1,27^ to calculate z-scores. Research staff or nurses measured weight and height/length in 3 studies,^1,27,28^ while 1 study relied on maternal report of infant weight.^26^ The age at which the outcomes were measured varied from approximately age 12 months^26^ to 5 years.^28^

#### Synthesis of the evidence

Among the 4 articles that met inclusion criteria, 2 studies reported that consumption of 100% juice was significantly associated with a measure of growth or risk of obesity,^26,28^ while 2 did not detect an association^1,27^ (Table 30). First, Gaffney et al.^26^ found that a higher intake frequency of 100% juice (greater than 1 feeding of juice per 2 days versus none) from age 6 to 12 months was significantly associated with higher WAZ at age 12 months; the comparison between the 2 lowest frequency groups (1 feeding of juice per 2 days versus none) was in the same direction but was statistically non-significant. Vandyousefi et al.^28^ found that consumption of any 100% fruit juice up to age 1 year was significantly associated with higher odds of obesity at age 2 to 5 years when compared to no consumption of either 100% fruit juice or SSBs; when overweight was examined as an outcome, the results were statistically non-significant but had the same directionality. The remaining 2 studies did not detect a statistically significant association between 100% juice consumption up to age 24 months and outcomes.^1,27^ While 1 study reported a non-significant higher risk of WLZ ≥1 at age 11–36 months with greater increases in 100% juice consumption,1 the other study reported minimal differences in BMIZ at age 36 months by 100% juice consumption.^27^

These 4 articles were also included as part of a larger systematic review with meta-analysis on 100% juice intake and growth, body composition, and risk of obesity * throughout the lifespan. Contribution of these studies in infants and young children, up to age 24 months, to the meta-analyses were relatively minimal due to the small number of studies and/or lack of data compatibility. Ultimately, 1 article^27^ was included in a single meta-analysis that examined 100% juice intake at baseline (analyzed categorically) and BMIZ at follow-up. Details on the full quantitative synthesis are presented in the systematic review report for 100% juice intake and growth, body composition, and risk of obesity.

* Deierlein AL, Raynor HA, Andres A, . 100% Juice and Growth, Body Composition, and Risk of Obesity: A Systematic Review with Meta-Analysis U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review; 2024. 10.52570/NESR.DGAC2025.SR05

#### Conclusion statement and grade

The Committee did not draw a conclusion statement about the relationship between 100% juice consumption by infants and young children, up to age 24 months, and growth, body composition, and risk of obesity (Table 29). This was primarily due to substantial concerns with consistency and precision in the body of evidence. First, the available evidence had inconsistent results, which was further exacerbated by the use of different outcome measures for each study. Additionally, the available evidence was limited by imprecision, due to the small number of studies and lack of information on power. Publication bias may be a limitation, but the small body of evidence makes it difficult to assess. Additionally, while the literature search was comprehensive, a search of the gray literature was not done, which could increase the possibility of publication bias. The risk of bias assessments for the included studies are presented in Table 31. Several risk of bias concerns were noted across all or most studies including risk of bias due to confounding, exposure measurement, missing data, and selection of reported results due to a lack of available pre-registered protocols or analysis plans.

Table 29 Conclusion statement, grade for 100% juice consumption by infants and young children and growth, body composition, and risk of obesity

Conclusion Statement | A conclusion statement cannot be drawn about the relationship between 100% juice consumption by infants and young children, up to age 24 months, and outcomes related to growth patterns, body composition, and risk of obesity during childhood because of substantial concerns with consistency and precision in the body of evidence.
Grade | Grade Not Assignable
Body of Evidence | 4 articles: 4 prospective cohort studies
Rationale | A small number of studies examined this exposure-outcome relationship. The study results were inconsistent and difficult to compare due to different outcome measures.

Table 30 Evidence examining the relationship between 100% juice consumption and growth, body composition, and risk of obesity ^a^

Study and Participant Characteristics | Exposure, Comparator, and Outcome | Results | Key Confounders, Model Adjustments, Funding
Amaro-Rivera, 2019 (https://pubmed.ncbi.nlm.nih.gov/31260549/)^1^; PCS, U.S. (Puerto Rico); [underlined: Analytic N] = 68 (Excluded participants lost to follow-up); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race/ethnicity:] Hispanic: 100%; [underlined: Maternal education:] ≤HS: 32.5%, >HS: 67.5%; [underlined: Other SEP measure(s):] WIC participation: 100%; [underlined: Maternal age:] Parent’s age: <30 y: 55.8%, ≥30 y: 44.2%; [underlined: Milk feeding practices:] EBF for ≥1 mo: 51%, Ever FF: 70.1%, Any BF at ~10 mo: 20.8%; [underlined: Child sex (female):] 47%; [underlined: Birth size:] NR; [underlined: Gestational age:] NR | [underlined: Exposure(s) and comparator(s):] Annual change in 100% juice Diet Quality Index Score; continuous; [underlined: Dietary assessment methods:] Interviewer-administered questionnaire completed by caregivers. Diet Quality Index Score based on semi-quantitative FFQ.; [underlined: Age(s) at dietary assessment:] 0–5, 8–36 mo; [underlined: Amounts consumed:] NR; [underlined: Outcome(s):] WLZ (≥1); [underlined: Outcome assessment methods:] Weight and length measured by trained research staff. Weight status assessed using WHO age- and sex-specific WLZ growth charts. Relative risk for WLZ (≥1 z-score vs <1 z-score), with underweight defined as WLZ ≤-2 SD, healthy weight status defined as WLZ >-2 and <1 SD, risk of overweight defined as WLZ between 1-<2, and overweight or obesity defined as WLZ ≥2 SD.; [underlined: Age(s) at outcome assessment:] 11–36 mo (Median: 21 mo, 11–23 mo: 61.0%, 24–36 mo: 39.0%) | [underlined: WLZ (≥1 vs <1) @ 11–36 mo (RR (95% CI))] 100% Juices score: 1.15 (0.98, 1.34) | [underlined: Key confounders accounted for:] SEP; sex; race and/or ethnicity; milk feeding practices; baseline anthropometry; [underlined: Key confounders NOT accounted for:] gestational age; [underlined: Model adjustments:] WLZ at baseline; [underlined: Funding:] University of Puerto Rico Central Administration Grant; Capacity Advancement in Research Infrastructure; NIMHD
Gaffney, 2012 (https://pubmed.ncbi.nlm.nih.gov/22233459/)^26^; PCS, IFPS II, U.S.; [underlined: Analytic N] = 691 (Excluded participants without weight data from 12 mo survey, with missing data for essential variables, or with biologically impossible observations for WAZ); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race/ethnicity:] White: ~95%, Hispanic: ~4%, Black: ~2%; [underlined: Maternal education:] HS or less: 14.6%, Some college: 34.3%, 4-y college or more: 51.1%; [underlined: Other SEP measure(s):] Household income (% of poverty line): <185%: 24.7%, 185–349%: 31.4%, >349%: 43.8%; [underlined: Maternal age:] 18–24 y: 10.1%, 25–34 y: 69.6%, >34 y: 20.3%; [underlined: Milk feeding practices:] BF intensity 6–12 mo: Low (<20% milk feedings from BM): 52.1%, Medium (20–80% milk feedings from BM): 24.3%, High (>80% milk feeding from BM): 23.6%; [underlined: Child sex (female):] 49%; [underlined: Birth weight:] 7.65 (1.02) lb;k; [underlined: Gestational age:] 100% born after 35 wk | [underlined: Exposure(s) and comparator(s):] Juice (100% fruit or 100% vegetable juice) ^b^ consumption frequency in late infancy (6–12 mo): 0 (ref), 1 feeding of juice per 2 d, >1 feeding of juice per 2 d; [underlined: Dietary assessment methods:] Maternal questionnaire; [underlined: Age(s) at dietary assessment:] 6, 7, 9, 10, and 12 mo (types/amounts); [underlined: Amounts consumed:] 0: 21.3%, 1 per 2 d: 35.2%, >1 per 2 d: 43.6%; [underlined: Outcome(s):] WAZ; [underlined: Outcome assessment methods:] Maternal report of weight and age at most recent doctor's visit. WAZ calculated using age and sex-specific growth reference data from CDC.; [underlined: Age(s) at outcome assessment:] 12 mo | [underlined: WAZ @ 12 mo (β)]; None (ref); 1 per 2 d: 0.21, p=NS; >1 per 2 d: 0.25, p<0.05 | [underlined: Key confounders accounted for:] SEP; sex; race and/or ethnicity; milk feeding practices; [underlined: Key confounders NOT accounted for:] gestational age; baseline anthropometry; [underlined: Model adjustments:] Bottle-to-bed behavior, BF intensity in late infancy, birth weight, mother's smoking status, weight gain during pregnancy, mother's age, mother's pregravid BMI, mother's education, mother's race/ethnicity, household income, juice consumption intensity (for timing of any), introduction to complementary foods (for types/amounts); [underlined: Funding:] NR
Mahoney, 2018 (https://pubmed.ncbi.nlm.nih.gov/29607793/)^27^; PCS, Born in Bradford 1000, U.K.; [underlined: Analytic N] = 12 mo: 722; 18 mo: 779 (Excluded participants with multiple births, missing child dietary data or outcome data, and not of White British or Pakistani ethnicity); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race/ethnicity:] Pakistani: 56%, White British: 44%; [underlined: Maternal education:] NR; [underlined: Other SEP measure(s):] NR; [underlined: Maternal age:] NR; [underlined: Milk feeding practices:] NR; [underlined: Child sex (female):] NR; [underlined: Birth weight:] 3,234.15 (521.97) g; [underlined: Gestational age:] NR | [underlined: Exposure(s) and comparator(s):] Pure fruit juices and baby fruit juices (Consumer vs non-consumer at 12 mo, ≤ vs > Median at 18 mo); [underlined: Dietary assessment methods:] FFQ completed by parents; [underlined: Age(s) at dietary assessment:] 12, 18 mo; [underlined: Amounts consumed:] Frequency at 12, 18 mo, respectively (Median, IQR): Pure fruit juice per wk: 0.0 (0.0, 0.5), 7.0 (0.0, 7.0); Outcome(s): BMIZ; [underlined: Outcome assessment methods:] Height, weight measured by trained researchers. Age- and sex-adjusted BMI calculated based on WHO 2006 standards.; [underlined: Age(s) at outcome assessment:] 36 mo | [underlined: BMIZ @ 36 mo (β (95% CI))]; Intake @ 12 mo:; Consumer vs non-consumer (ref): −0.05 (−0.20, 0.10), p=0.53; Intake @ 18 mo:; >7.0/wk vs ≤7.0/wk (ref): −0.07 (−0.21, 0.08), p=0.37 | [underlined: Key confounders accounted for:] Sex; race and/or ethnicity; baseline anthropometry; [underlined: Key confounders NOT accounted for:] SEP; milk feeding practices; gestational age; [underlined: Model adjustments:] Ethnicity, sex, birth weight, other key indicator food groups (formula milk; commercial savoury baby foods; commercial sweet baby foods; chips, roast and potato shapes; processed meat products; vegetables; fruit; cakes, biscuits, chocolate and sweets; crisps and savoury snacks; sugar-sweetened drinks; pure fruit juice; low-sugar drinks; water); [underlined: Funding:] NIHR
Vandyousefi, 2021 (https://pubmed.ncbi.nlm.nih.gov/33495846/)^28^; PCS, SWIFT, U.S.; [underlined: Analytic N] = 835 (Excluded participants with missing data on BF, infant dietary intake variables from birth to 1 y, sociodemographics, prenatal and newborn clinical outcomes, and child weight and height measures at 2–5 y, and mothers who had overt diabetes at study baseline); [underlined: Adequately powered:] NR; Participant Characteristics (Mean (SD) unless otherwise noted); [underlined: Race/ethnicity:] Non-Hispanic Asian: 37%, Hispanic: 30%, Non-Hispanic White: 23%, Non-Hispanic Black: 8%, Mixed race/other: 2%; [underlined: Maternal education:] 14.9 (2.9) y; [underlined: Other SEP measure(s):] Private insurance: 100%; WIC recipient: 25%; [underlined: Maternal age:] 33.4 (4.8) y; [underlined: Milk feeding practices:] Any BF duration: 9 (7.2) mo; BF duration <6 mo: 40%, ≥6 mo: 60%; BF intensity at 6–9 wk: EBF: 22%, Mostly BF: 41%, Mixed/inconsistent FF: 21%, Exclusively or mostly FF: 16%; BF intensity and duration at 12 mo: <6: 53%, ≥6: 47%; [underlined: Child sex (female):] 48%; [underlined: Birth weight:] 3,397 (499) g; [underlined: Birth length:] 50.5 (2.4) cm; [underlined: Size-at-birth percentile:] LGA: 21%, AGA: 77%, SGA: 2%; [underlined: Gestational age:] 39 (1.2) wk; [underlined: Other relevant characteristics:] GDM: 100%; Pre-pregnancy BMI: child normal weight: 28.5 (6.8), child overweight: 31.7 (8.3), child obesity: 33.6 (7.1), p<0.001 | [underlined: Exposure(s) and comparator(s):] 100% fruit juice (unsweetened/with no added sugar) only, SSB (any sugary drinks, Pedialyte, water or juices with added sugar) only, SSB or 100% fruit juice, no SSB/100% juice intake (ref) from birth to 1 y; [underlined: Dietary assessment methods:] Maternal surveys of date of introduction of solids, fruit juice, sweetened beverages, water, sugar water, and other beverages, including types and amounts of each item.; [underlined: Age(s) at dietary assessment:] 6–9 wk, 1 y, 2 y post baseline (in-person surveys); Monthly from delivery to 1 y (mailed surveys); [underlined: Amounts consumed:] Beverage intake from birth to 1 y: No SSB/no 100% fruit juice: 33%, 100% fruit juice: 51%, SSB: 16%; [underlined: Outcome(s):] Overweight, Obesity; [underlined: Outcome assessment methods:] Weight and length obtained from Electronic Health Records during well check visits. Age- and sex-standardized BMI percentiles calculated based on CDC growth percentiles. Overweight defined as BMI-for-age 85th-<95th percentile. Obesity defined as BMI-for-age ≥95th percentile.; [underlined: Age(s) at outcome assessment:] 2–5 y | [underlined: Overweight @ 2–5 y (OR (95% CI))]; No SSB/no 100% fruit juice (ref); 100% fruit juice: 1.24 (0.78, 1.98), p=0.48; SSB: 1.31 (0.69, 2.50), p=0.67; [underlined: Overweight @ 2–5 y, Adequate BF (OR (95% CI))]; No SSB/no 100% fruit juice (ref); 100% fruit juice: 1.23 (0.73, 2.34), p=0.65; SSB: 1.31 (0.51, 2.94), p=0.65; SSB or 100% fruit juice: 1.28 (0.71, 2.18), p=0.38; [underlined: Overweight @ 2–5 y, Adequate EBF (OR (95% CI))]; No SSB/no 100% fruit juice (ref); 100% fruit juice: 1.28 (0.73, 2.27), p=0.39; SSB: 1.26 (0.73, 2.18), p=0.72; SSB or 100% fruit juice: 1.05 (0.55, 1.99), p=0.43; [underlined: Obesity @ 2–5 y (OR (95% CI))]; No SSB/no 100% fruit juice (ref); 100% fruit juice: 2.18 (1.17, 4.06), p=0.02; SSB: 3.22 (1.55, 6.67), p<0.01; [underlined: Obesity @ 2–5 y, Adequate BF (OR (95% CI))]; No SSB/no 100% fruit juice (ref); 100% fruit juice: 3.13 (1.11, 7.29), p=0.03; SSB: 3.35 (1.32, 8.50), p=0.01; SSB or 100% fruit juice: 3.32 (1.29, 8.25), p<0.01; [underlined: Obesity @ 2–5 y, Adequate EBF (OR (95% CI))]; No SSB/no 100% fruit juice (ref); 100% fruit juice: 4.17 (1.55, 11.17), p<0.01; SSB: 4.71 (1.43, 15.01), p<0.01; SSB or 100% fruit juice: 4.45 (1.40, 8.47), p<0.01 | [underlined: Key confounders accounted for:] SEP; sex; race and/or ethnicity; milk feeding practices; [underlined: Key confounders NOT accounted for:] gestational age; baseline anthropometry; [underlined: Model adjustments:] Maternal education level, race/ethnicity, gestational weight gain, prenatal 3 h 100 g OGTT sum of 4 z-scores, GDM treatment type, gestational age at GDM diagnosis, WIC participation, parity, infant sex, infant size for gestational age, sex at birth, and age at BMI measurement; [underlined: Funding:] NIDDK; NICHD; ADA

a Abbreviations: @: at; AGA: appropriate for gestational age; β: beta; BF: breastfeeding; BM: breast milk; BMI: body mass index; BMIZ, BMI z-score; CDC: Centers for Disease Control and Prevention; CI: confidence interval; cm: centimeter; d: day; EBF: exclusive breastfeeding; FF: formula feeding; FFQ: food frequency questionnaire; g: gram; GDM: gestational diabetes mellitus; HS: high school; IFPS II: Infant Feeding Practices Study II; IQR: interquartile range; LGA: large for gestational age; mo: month; NR: not reported; OGTT: oral glucose tolerance test; OR: odds ratio; oz: ounce; PCS: prospective cohort study; ref: reference; RR: risk ratio; SD: standard deviation; SEP: socioeconomic position; SGA: small for gestational age; SSB: sugar-sweetened beverage; SWIFT: Study of Women, Infant Feeding and Type 2 Diabetes after GDM; U.K.: United Kingdom; U.S.: United States; vs: versus; WAZ: weight-for-age z-score; WIC: Special Supplemental Nutrition Program for Women, Infants, and Children; WHO: World Health Organization; wk: week; WLZ: weight-for-length z-score; y: year

b Questionnaires: Infant Feeding Practices Study II and Its Year Six Follow-Up. Centers for Disease Control and Prevention. Updated April 4, 2023. Accessed December 15, 2023. https://www.cdc.gov/breastfeeding/data/ifps/questionnaires.htm .

Table 31 Risk of bias for observational studies examining 100% juice consumption and growth, body composition, and risk of obesity^a^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Amaro-Rivera, 2019^1^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Gaffney, 2012^26^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | HIGH | SOME CONCERNS | SOME CONCERNS | HIGH
Mahoney, 2018^27^ | HIGH | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Vandyousefi, 2021^28^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH

a Possible ratings of low, some concerns, high, very high, no information, or not applicable determined using the "Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)" tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602. ) *Low risk of bias except for concerns about uncontrolled confounding.

### Fruit

#### Description of the evidence

Five studies (from 6 articles) met inclusion criteria and examined the relationship between fruit consumption up to age 24 months and growth, body composition, and risk of obesity (Table 33).^1,6,27,29–3^,^1^ All studies were PCS, using data from the following cohorts: Born in Bradford 1000 study,^27^ Childhood Asthma Prevention Study (CAPS),^29,30^ the Longitudinal Twin Study (LoTiS),31 WIC ITFPS-2,^6^ and 1 unnamed cohort.^1^ One study that was a secondary analysis of an RCT testing the effect of dust mite avoidance and omega-3 supplementation on asthma prevention.^29,30^

##### Population

Two studies were conducted in the United States,^1,6^ including 1 study conducted in Puerto Rico,^1^ and 1 study each was conducted in Australia,^29,30^ China,31 the United Kingdom.^27^ The analytic sample sizes ranged from 681 to 1,872.^6^ No studies reported having sufficient power related to fruit intake and the relevant outcomes.

Race and/or ethnicity varied across studies, including 1 study with 100% Hispanic participants,^1^ 2 studies with approximately half Caucasian^29,30^ or White British^27^ participants, and 1 study with approximately 41% Hispanic, 29% non-Hispanic White, and 25% non-Hispanic African American participants.^6^ A variety of measures of SEP were reported across the studies. Maternal education varied with 37.5%^6^ and 67.5%^1^ completing high school in 2 studies, and 52% receiving tertiary education in a third, Australian study.^29^ Two studies exclusively included mothers who were participating in WIC,^1,6^ 1 of which also reported that 64% of participants had an income less than or equal to 75% of the poverty guideline.^6^ Another study reported that 87% of fathers and 49% of mothers had full-time employment,^29^ while another study reported 22% of mothers were employed at 6 months.^6^ Maternal age was, on average, approximately 30 years in 2 studies,^29,31^ while 1 study reported that 44% of participants were age 30 years or older1 and 47% of mothers were age 26 years or older in another.^6^ Human milk and infant formula feeding practices varied across studies: 51% of infants were exclusively breastfed at 1 month in 1 study,^1^ 82% received any breast milk in another,^6^ 42% of children were breastfed at 6 months in a third study,^29,30^ and the mean breastfeeding duration was 7.6 months in a fourth.^31^

The studies noted that approximately 50% were female.^1,6,29–3^,^1^ Regarding birth weight, 1 study noted that the majority of infants were born weighing between 2.5 and 4.5 kilograms,^6^ while the mean birth weight was 3.2^27^ and 3.5 kilograms^30^ in 2 additional studies. The average birth weight was 2.5 kilograms in a fourth study conducted exclusively among twins^31^ Gestational age was reported in 3 studies, with 2 excluding infants born preterm while the third, conducted exclusively with twins, reported that 53.2% of the infants were born preterm.^31^ Among the 2 studies that reported baseline anthropometry, 1 reported that 12.7% had overweight at age 12 months,^31^ while the other reported that the average weight was 11.6 kilograms at age 18 months.^30^

##### Exposures and comparators

All studies assessed the amounts or frequency of fruit consumption up to 24 months,^1,6,27,29–3^,^1^ none of which specified the types of fruit that were included in the measure. Most studies analyzed a continuous measure of the amount or frequency of fruit consumption,^1,6,29–31^ except for 1 study that compared fruit consumption greater than, to less than or equal to, the median frequency.^27^ The studies used a variety of assessment methods to measure fruit consumption. Three studies used a FFQ,^1,27,3^,^1^ 1 study used a 3-day weighed food record,^29,30^ and 1 study used a 24-hour recall.^6^ Half of the studies assessed fruit intake multiple times up to age 24 months,^1,6,27^ with 2 studies assessing fruit intake before age 12 months,^1,6^ and all studies assessing fruit intake at age 12 months or older.^1,6,27,29–3^,^1^

##### Outcomes

Four studies examined growth,^6,27,29–31^ 2 studies examined body composition,^30,31^ and 1 study examined risk of overweight.^1^ The outcomes were measured by trained personnel in all studies. The most common outcome measure was BMIZ or BMI (including trajectories or measures of change), which were assessed in all 4 studies. Other outcomes examined included weight and length increment,^31^ WAZ,^31^ HAZ,^31^ waist circumference,^30^ body fat mass and percentage,^31^ and the odds of having a WLZ greater than or equal to 1.^1^ BMIZ were based on WHO growth standards^27^ and the CDC growth charts.^6,29^ The age at outcome assessment ranged from age 11 months^1^ to 11.5 years.^29^

#### Synthesis of the evidence

All 4 studies that examined growth reported exclusively or predominantly null associations with fruit consumption across a variety of outcomes from birth to 11.5 years (Table 33).^6,27,29–31^ The direction of these relatively small effect sizes tended to show that greater fruit intake is non-significantly associated with higher levels of growth.^27,30,31^ However, the single study that detected a statistically significant association between fruit consumption and growth reported that greater frequency of fruit consumption at age 9 months was associated with lower BMIZ at age 2 years, but not at age 3 or 4 years.^6^

Few studies examined body composition^30,31^ or the risk of obesity,^1,30,31^ and the outcomes were inconsistent across studies. One study reported a statistically significant association between greater fruit consumption at age 18 months and higher waist circumference at age 8 years, but the utility of this measure in this age group is limited.^30^ The remaining studies did not detect a relationship between fruit consumption and body composition^31^ or risk of overweight.^1^

#### Conclusion statements and grades

The Committee developed a conclusion statement about the relationship between fruit consumption and growth based on their review of the body of evidence (Table 32). The grade reflects the strength of the evidence underlying the conclusion statement. However, the Committee did not draw a conclusion statement about the relationship between fruit consumption and body composition and risk of obesity because there is not enough available evidence (Table 32). The risk of bias assessments for the studies that addressed this question are documented in Table 34.

Table 32 Conclusion statement, grade for fruit consumption by infants and young children and growth, and consumption of fruit by infants and young children and body composition and risk of obesity

Conclusion Statement | Fruit consumption by infants and young children, up to age 24 months, is not associated with unfavorable outcomes related to growth patterns during childhood. This conclusion is based on evidence graded as limited.
Grade | Limited
Body of Evidence | 5 articles (4 studies): 4 prospective cohort studies
Consistency | Minimal concerns with consistency.
Precision | Some concerns due to few included studies and relatively wide confidence intervals; power calculated were not reported.
Risk of bias | Substantial concerns with risk of bias, particularly due to confounding and missing data.
Directness | Minimal concerns with directness.
Generalizability | Some concerns with applicability to the U.S. population due to few studies were conducted in the United States.
Conclusion Statement | A conclusion statement cannot be drawn about the relationship between fruit consumption by infants and young children, up to age 24 months, and body composition and risk of obesity during childhood because there is not enough evidence available.
Grade | Grade Not Assignable
Body of Evidence | 3 articles: 3 prospective cohort studies
Rationale | There is not enough evidence available to answer this question.

#### Assessment of the evidence

The body of evidence underlying the graded conclusion statement above includes 5 articles from 4 PCS. The evidence was graded based on an assessment of 5 grading elements, as described below. Publication bias was also a consideration; however, this was not assessed as a serious concern because the body of evidence included studies that reported only nonsignificant findings as well as studies that reported a mix of both significant and nonsignificant results, across a range of analytic sample sizes. However, while the literature search was comprehensive, a search of the gray literature was not done, which could increase the possibility of publication bias.

##### Consistency

Studies consistently reported null associations between fruit consumption by infants and young children and growth. The studies also examined relatively consistent exposures and outcomes assessed.

##### Precision

Only 4 studies were examined the relationship between fruit consumption by infants and young children and outcomes related to growth. The analytic sample sizes ranged from 302 to 1,872, but the confidence intervals, when reported, were relatively wide. No studies reported a power calculation.

##### Risk of bias

There were several risk of bias concerns across the body of evidence (Table 34). Most of the studies had high risk of bias due to confounding because studies did not account for most of the key confounders. One study had a very high risk of bias due to confounding because of a lack of any model adjustments. Most studies had some concerns or high risk of bias due to missing data because of high rates of missing data which was not accounted for. Finally, all studies had some concerns or high risk of bias due to selection of the reported result because none reported a pre-registered protocol or analysis plan.

##### Directness

The studies examined exposures and outcomes that aligned with the analytic framework.

##### Generalizability

There were some concerns with generalizability to the U.S. population due to few studies being conducted in the United States.

Table 33 Evidence examining the relationship between fruit consumption and growth, body composition, and risk of obesity ^a^

Study and Participant Characteristics | Exposure, Comparator, and Outcome | Results | Key Confounders, Model Adjustments, Funding
Amaro-Rivera, 2019 (https://pubmed.ncbi.nlm.nih.gov/31260549/)^1^; PCS, U.S. (Puerto Rico); [underlined: Analytic N] = 68 (Excluded participants lost to follow-up); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race/ethnicity:] Hispanic: 100%; [underlined: Maternal education:] ≤HS: 32.5%, >HS: 67.5%; [underlined: Other SEP measure(s):] WIC participation: 100%; [underlined: Maternal age:] Parent’s age: <30 y: 55.8%, ≥30 y: 44.2%; [underlined: Milk feeding practices:] EBF for ≥1 mo: 51%, Ever FF: 70.1%, Any BF at ~10 mo: 20.8%; [underlined: Child sex (female):] 47%; [underlined: Birth size:] NR; [underlined: Gestational age:] NR | [underlined: Exposure(s) and comparator(s):] Annual change in fruits Diet Quality Index Scores; amount, continuous; [underlined: Dietary assessment methods:] Interviewer-administered questionnaire completed by caregivers. Diet Quality Index Score based on FFQ.; [underlined: Age(s) at dietary assessment:] 0–5, 8–36 mo; [underlined: Amounts consumed:] NR; [underlined: Outcome(s):] WLZ (≥1 vs <1); [underlined: Outcome assessment methods:] Weight and length measured by trained research staff.; Weight status assessed using WHO age- and sex-specific WLZ growth charts. Relative risk for WLZ (≥1 z-score vs <1 z-score), with underweight defined as WLZ ≤-2 SD, healthy weight status defined as WLZ >-2 and <1 SD, risk of overweight defined as WLZ between 1-<2, and overweight or obesity defined as WLZ ≥2 SD.; [underlined: Age(s) at outcome assessment:] 11–36 mo (Median: 21 mo, 11–23 mo: 61.0%, 24–36 mo: 39.0%) | [underlined: WLZ (≥1 vs <1) @ 11–36 mo (RR (95% CI))]; Fruits score: 0.92 (0.72, 1.17) | [underlined: Key confounders accounted for:] SEP; sex; race and/or ethnicity; milk feeding practices; baseline anthropometry; [underlined: Key confounders NOT accounted for:] gestational age; [underlined: Model adjustments:] Weight-for-length z-score at baseline; [underlined: Funding:] University of Puerto Rico Central Administration Grant; Capacity Advancement in Research Infrastructure; NIMHD
Au, 2023 (https://pubmed.ncbi.nlm.nih.gov/36806452/)^6^; PCS, WIC ITFPS-2, U.S.; [underlined: Analytic N] = 1,523 (24 mo), 1,680 (36 mo), 1,872 (48 mo) (Excluded participants with missing data on HEI-2015 or BMI at 2, 3, or 4 y, born prematurely, had very low birth weight, or had long-term medical problems that could affect eating.); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race/ethnicity:] Hispanic: 40.6%, Non-Hispanic White: 29.1%, Non-Hispanic African American: 24.8%, Non-Hispanic Other: 5.5%; [underlined: Maternal education:] <HS: 24.4%, HS: 37.7%, >HS: 37.5%; [underlined: Other SEP measure(s):] Participating in WIC: 100%; Maternal employment at 6 mo: Full-time: 21.5%, Part-time: 20.2%, Not working for pay: 58.2%; Poverty level at enrollment: ≤75% of poverty guideline: 64.0%, >75-<130%: 26.3%, >130% poverty: 9.7%; [underlined: Maternal age:] 16–19 y: 11.7%, 20–25 y: 41.1%, ≥26 y: 47.3%; [underlined: Milk feeding practices:] Any BF: 81.9%; Any formula use: 95.5%; [underlined: Child sex (female):] 49%; [underlined: Birth weight:] Low (<2.5 kg): 5.3%, Normal (2.5-≤4.5 kg): 93.4%, High (>4.5 kg): 1.3%; [underlined: Gestational age:] Excluded infants born prematurely | [underlined: Exposure(s) and comparator(s):] Fruit (frequency, continuous, Infant Diet Quality Index component score from 0–1 based on degree of adherence to guidelines; max score: ≥2x/d at 9 mo); [underlined: Dietary assessment methods:] 24-h dietary recall via telephone interview with caregiver; [underlined: Age(s) at dietary assessment:] 1, 3, 5, 7, 9 11, 13, 15, 18, 24, 30, 36, 42, and 48 mo; [underlined: Amounts consumed:] ≥2x/d at 9 mo: 47.4%, None at 9 mo: 16.6%; [underlined: Outcome(s):] BMIZ; [underlined: Outcome assessment methods:] Weight and length/height collected at WIC sites or from child’s health care provider. BMIZ based on CDC age- and sex-specific growth charts; [underlined: Age(s) at outcome assessment:] 2, 3, 4 y | [underlined: BMIZ @ 2, 3, 4 y]; 2 y: Greater adherence to guidelines associated with lower BMIZ, p<0.05; 3 y: Data NR, p>0.10; 4 y: Data NR, p>0.10 | [underlined: Key confounders accounted for:] SEP; sex; gestational age; [underlined: Key confounders NOT accounted for:] milk feeding practices; baseline anthropometry; [underlined: Model adjustments:] None; [underlined: Funding:] NHLBI; USDA/NIFA
Garden, 2011 (https://pubmed.ncbi.nlm.nih.gov/21346718/)^30^; PCS, CAPS, Australia; [underlined: Analytic N] = 362 (Excluded participants with missing data on diet or anthropometrics); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race/ethnicity:] Grandparents ethnicity/country of birth: Caucasian: 55%, European: 9%, Middle Eastern: 4%, Indian: 5%, Asian: 4%, Undefined: 24%; [underlined: Maternal education:] NR; [underlined: Other SEP measure(s):] Paternal education: ≤10 y: 33%, 11–12 y: 18%, Tertiary education: 48%; [underlined: Maternal age:] NR; [underlined: Milk feeding practices:] BF ≥6 mo: 42%; [underlined: Child sex (female):] 49%; [underlined: Birth weight:] 3,493 (492) g; [underlined: Gestational age:] NR; [underlined: Other relevant characteristics:] Secondary analysis of RCT (testing intervention of house dust mite avoidance and omega-3 supplementation); all children recruited at increased risk of developing asthma | [underlined: Exposure(s) and comparator(s):] Fruit (amount, continuous, as quintiles); [underlined: Dietary assessment methods:] 3-d weighed food records completed by parent/caregiver; [underlined: Age(s) at dietary assessment:] 18 mo; [underlined: Amounts consumed:] Quintiles of fruit intake g: 0, 17, 45, 80, 124 % total energy intake: 0, 1, 3, 5, 8; [underlined: Outcome(s):] BMI, waist circumference; [underlined: Outcome assessment methods:] Weight, length, and waist circumference measured by study nurses; [underlined: Age(s) at outcome assessment:] 8 y | [underlined: BMI @ 8 y (Coefficient (95% CI))]; Per quintile; g: 0.17 (−0.04, 0.38), p for trend=0.11; % of total energy: 0.18 (−0.03, 0.39), p for trend=0.09; [underlined: WC @ 8 y (Coefficient (95% CI))]; Per quintile; g: 0.63 (0.05, 1.20), p for trend=0.03; % of total energy: 0.56 (0.00, 1.12), p for trend=0.05 | [underlined: Key confounders accounted for:] SEP; sex; race and/or ethnicity; milk feeding practices; gestational age; [underlined: Key confounders NOT accounted for:] baseline anthropometry; [underlined: Model adjustments:] sex, asthma study intervention group, birth weight, breastfeeding for at least 6 mo, parental obesity status, ethnicity, smoking in pregnancy and father’s education, total energy intake (food intake in g only); [underlined: Funding:] The National Health and Medical Research Council of Australia; Cooperative Research Centre for Asthma; New South Wales Department of Health; Children’s Hospital Westmead; University of Sydney, Faculty of Medicine; Commonwealth Department of Health and Aging
Garden, 2012 (https://pubmed.ncbi.nlm.nih.gov/23201761/)^29^; PCS, CAPS, Australia; [underlined: Analytic N] = 298 (Excluded participants who were not still participating in the study at 11.5 y or did not have dietary data.); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race/ethnicity:] NR (Australian born mother: 74%, Australian born father: 69%; Child’s grandparents ethnicity/country of birth: Caucasian: ~54%, European: ~9%, Middle Eastern/Indian/Asian: ~12%, Undefined: ~25%); [underlined: Maternal education:] 52% tertiary educated; [underlined: Other SEP measure(s):] Full-time employment: Mother: 49%, Father: 87%; [underlined: Maternal age:] 29.0 (5.1) y; [underlined: Milk feeding practices:] BF duration: 0 to <3 mo: 40%, 3 to <6 mo: 16.8%, ≥6 mo: 43.2%; [underlined: Child sex (female):] 49%; [underlined: Birth weight:] 100% ≥2.5 kg; [underlined: Gestational age:] 100% ≥36 wk; [underlined: Other relevant characteristics:] Secondary analysis of RCT (testing intervention of house dust mite avoidance and omega-3 supplementation); all children recruited at increased risk of developing asthma | [underlined: Exposure(s) and comparator(s):] Fruit (amount, continuous); [underlined: Dietary assessment methods:] 3-d weighed food record (2 weekdays and 1 weekend day) completed by parent/caregiver; [underlined: Age(s) at dietary assessment:] 18 mo; [underlined: Amounts consumed:] See results for intake data; [underlined: Outcome(s):] BMI trajectory; [underlined: Outcome assessment methods:] Weight and height measured by study nurses. Three BMI trajectories defined using latent basis growth mixture model in relationship to CDC percentiles, stratified by sex.; [underlined: Age(s) at outcome assessment:] 1, 3, 6, 9, 12, 18 mo, 2–5 y (every 6 mo), 8 y, 11.5 y | [underlined: BMI trajectory @ birth-11.5 y (median intake at 18 mo by trajectory group)]; Boys: normal trajectory: 57.3 g, early and persistent trajectory: 78.0 g, late BMI increase: 79.7 g, p=0.20; Girls: normal trajectory: 60.7 g, early and persistent trajectory: 61.3 g, late BMI increase: 57.7 g, p=0.75; Results analyzed by % of total energy were similar. | [underlined: Key confounders accounted for:] SEP; sex; race and/or ethnicity; milk feeding practices; baseline anthropometry (multinomial regression only); [underlined: Key confounders NOT accounted for:] gestational age; [underlined: Model adjustments:] dietary intervention group, BF, parental obesity, ethnicity, smoking during pregnancy, father’s education status (multinomial regression only); [underlined: Funding:] National Health and Medical Research Council of Australia
Jin, 2022 (https://pubmed.ncbi.nlm.nih.gov/34412548/)^31^; PCS, LoTiS, China; [underlined: Analytic N] = 302 (Excluded participants lost to follow-up); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race/ethnicity:] NR; [underlined: Maternal education:] NR; [underlined: Other SEP measure(s):] NR; [underlined: Maternal age:] 30.47 (3.70) y; [underlined: Milk feeding practices:] BF duration: 7.60 (3.99) mo; Milk feeding at 12 mo: EBF: 4.6%, Exclusive FF: 73.7%, Mixed BF and FF: 21.7%; [underlined: Child sex (female):] 45%; [underlined: Birth weight:] 2.49 (0.45) kg; [underlined: Birth length:] 46.04 (2.40) cm; [underlined: SGA at birth:] 12.4%; [underlined: Gestational age:] 36.43 (1.48) wk; 53.2% born preterm; [underlined: Other relevant characteristics:] 100% twins (both included in analyses) | [underlined: Exposure(s) and comparator(s):] Fruits (frequency, continuous); [underlined: Dietary assessment methods:] FFQ completed by mother/guardian; [underlined: Age(s) at dietary assessment:] 12 mo; [underlined: Amounts consumed:] NR; [underlined: Outcome(s):] WAZ, HAZ, BMIZ, body fat mass, body fat mass percentage, weight increment (12–24 mo), length increment (12–24 mo), BMI increment (12–24 mo); [underlined: Outcome assessment methods:] Weight and height were measured by study personnel. Body fat was measured using bioimpedance.; [underlined: Age(s) at outcome assessment:] 12, 24 mo | [underlined: WAZ @ 24 mo (spearman correlation)]; 0.097, p=0.072; [underlined: HAZ @ 24 mo (spearman correlation)]; 0.061, p=0.288; [underlined: BMIZ @ 24 mo (spearman correlation)]; 0.089, p=0.053; [underlined: Weight increment from 12 to 24 mo (spearman correlation)]; 0.012, p=0.833; [underlined: Length increment from 12 to 24 mo (spearman correlation)]; –0.089, p=0.122; [underlined: BMI increment from 12 to 24 mo (spearman correlation)]; 0.025, p=0.685; [underlined: Body fat mass @ 24 mo (statistical measure NR, general linear model)] 0.053, p=0.509; [underlined: Body fat percentage @ 24 mo (statistical measure NR, general linear model)] 0.023, p=0.769 | [underlined: Key confounders accounted for:] sex (body fat mass and % body fat mass only); baseline anthropometry (growth increments only); [underlined: Key confounders NOT accounted for:] WAZ, HAZ, BMIZ: SEP; sex; race and/or ethnicity; milk feeding practices; gestational age; baseline anthropometry. Body fat mass, % body fat mass: SEP; race and/or ethnicity; milk feeding practices; gestational age; baseline anthropometry. Growth increments: SEP; sex; race and/or ethnicity; milk feeding practices; gestational age; [underlined: Model adjustments:] sex (body fat mass, % body fat); None (all other outcomes); [underlined: Funding:] National Key Research and Development Program of China; National Natural Science Foundation of China; Chongqing Joint Program of Science and Health; Key Disciplines of Medical and Health Research of Yuhang District of Hangzhou City
Mahoney, 2018 (https://pubmed.ncbi.nlm.nih.gov/29607793/)^27^; PCS, Born in Bradford 1000, U.K.; [underlined: Analytic N] = 12 mo: 722; 18 mo: 779 (Excluded participants with multiple births, missing child dietary data or outcome data, and not of White British or Pakistani ethnicity); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race/ethnicity:] Pakistani: ~56%, White British: ~44%; [underlined: Maternal education:] NR; [underlined: Other SEP measure(s):] NR; [underlined: Maternal age:] NR; [underlined: Milk feeding practices:] NR; [underlined: Child sex (female):] NR; [underlined: Birth weight:] 3,234.15 (521.97) g; [underlined: Gestational age:] NR | [underlined: Exposure(s) and comparator(s):] Fruit (frequency, ≤ vs > Median); [underlined: Dietary assessment methods:] FFQ completed by parents; [underlined: Age(s) at dietary assessment:] 12, 18 mo; [underlined: Amounts consumed:] Frequency at 12, 18 mo, respectively (Median, IQR): 1.9 (1.1, 2.9) x/d, 5.0 (4.0, 6.0) x/d; [underlined: Outcome(s):] BMIZ; [underlined: Outcome assessment methods:] Height, weight measured by trained researchers. Age- and sex-adjusted BMI calculated based on WHO 2006 standards.; [underlined: Age(s) at outcome assessment:] 36 mo | [underlined: BMIZ @ 36 mo (β (95% CI))]; Intake @ 12 mo: > vs ≤ 1.9x/d: 0.09 (−0.07, 0.25), p=0.25; Intake @ 18 mo: > vs ≤ 5.0x/d: −0.04 (−0.19, 0.11), p=0.60 | [underlined: Key confounders accounted for:] Sex; race and/or ethnicity; [underlined: Key confounders NOT accounted for:] SEP; milk feeding practices; gestational age; baseline anthropometry; [underlined: Model adjustments:] Ethnicity, sex, birth weight, other key indicator food groups (formula milk; commercial savoury baby foods; commercial sweet baby foods; chips, roast and potato shapes; processed meat products; vegetables; fruit; cakes, biscuits, chocolate and sweets; crisps and savoury snacks; sugar-sweetened drinks; pure fruit juice; low-sugar drinks; water); [underlined: Funding:] NIHR

a Abbreviations: @: at; β: beta; BF: breastfeeding; BMI: body mass index; BMIZ: BMI z-score; CAPS: Childhood Asthma Prevention Study; CDC: Centers for Disease Control and Prevention; CI: confidence interval; cm: centimeter; d: day; EBF: exclusive breastfeeding; FF: formula feeding; FFQ: food frequency questionnaire; g: gram; h: hour; HAZ: height-for-age z-score; HEI: Healthy Eating Index; HS: high school; IQR: interquartile range; LoTiS: Longitudinal Twin Study; mo: month; NR: not reported; NS: non-significant; PCS: prospective cohort study; RCT: randomized controlled trial; RR: risk ratio; SD: standard deviation; SEP: socioeconomic position; U.K.: United Kingdom; U.S.: United States; vs: versus; WAZ: weight-for-age z-score; WHO: World Health Organization; WIC: Special Supplemental Nutrition Program for Women, Infants, and Children; WIC-IFTPS-2: WIC Infant and Toddler Feeding Practices Study-2; wk: week; WLZ: weight-for-length z-score; x: times; y: year

Table 34 Risk of bias for observational studies examining fruit consumption and growth, body composition, and risk of obesity ^a^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Amaro-Rivera, 2019^1^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Au, 2023^6^ | HIGH | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Garden, 2011^30^ | SOME CONCERNS | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Garden, 2012^29^ | SOME CONCERNS | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Jin, 2022^31^ (body fat mass, % fat mass) | HIGH | SOME CONCERNS | LOW | LOW | LOW | LOW | HIGH | HIGH
Jin, 2021^31^ (BMIZ, HAZ, WAZ, growth increments) | VERY HIGH | SOME CONCERNS | LOW | LOW | LOW | LOW | HIGH | VERY HIGH
Mahoney, 2018^27^ | HIGH | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH

a Possible ratings of low, some concerns, high, very high, no information, or not applicable determined using the "Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)'' tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602. ) *Low risk of bias except for concerns about uncontrolled confounding.

### Vegetables

#### Description of the evidence

Five studies (from 6 articles) met inclusion criteria and examined the relationship between vegetable consumption among infants and young children, up to age 24 months, and growth, body composition, and risk of obesity (Table 36).^1,6,27,29–3^,^1^ All studies were PCS, using data from the following cohorts: Born in Bradford 1000 study,^27^ CAPS,^29,30^ LoTiS,^31^ WIC ITFPS-2,^6^ and 1 unnamed cohort.^1^ One study that was a secondary analysis of an RCT testing the effect of dust mite avoidance and omega-3 supplementation on asthma prevention.^29,30^

##### Population

Two studies were conducted in the United States,^1,6^ including 1 study conducted in Puerto Rico,^1^ and 1 study each was conducted in Australia,^29,30^ China,^31^ the United Kingdom.^27^ The analytic sample sizes ranged from 68^1^ to 1,872.^6^ No studies reported having sufficient power related to consumption of vegetables and the relevant outcomes.

Race and/or ethnicity varied across studies, including 1 study with 100% Hispanic participants,^1^ 2 studies with approximately half Caucasian^29,30^ or White British^27^ participants, and 1 study with approximately 41% Hispanic, 29% non-Hispanic White, and 25% non-Hispanic African American participants.^6^ A variety of measures of SEP were reported across the studies. Maternal education varied with 37.5%^6^ and 67.5%^1^ completing high school in 2 studies, and 52% receiving tertiary education in a third, Australian study.^29^ Two studies exclusively included mothers who were participating in WIC,^1,6^ 1 of which also reporting that 64% of participants had an income less than or equal to 75% of the poverty guideline.^6^ Another study reported that 87% of fathers and 49% of mothers had full-time employment,^29^ while another study reported 22% of mothers were employed at 6 months.^6^ Maternal age was, on average, approximately 30 years in 2 studies,^29,31^ while 1 study reported that 44% of participants were age 30 years or older^1^ and 47% of mothers were age 26 years or older in another.^6^ Human milk and infant formula feeding practices varied across studies: 51% of infants were exclusively breastfed at 1 month in 1 study,^1^ 82% received any breast milk in another,^6^ 42% of children were breastfed at 6 months in a third study,^29,30^ and the mean breastfeeding duration was 7.6 months in a fourth.^31^

The studies noted that approximately 50% were female.^1,6,29–3^,^1^ Regarding birth weight, 1 study noted that the majority of infants were born weighing between 2.5 and 4.5 kilograms,^6^ while the mean birth weight was 3.2^27^ and 3.5 kilograms^30^ in 2 additional studies. The average birth weight was 2.5 kilograms in a fourth study conducted exclusively among twins^31^ Gestational age was reported in 3 studies, with 2 excluding infants born preterm while the third, conducted exclusively with twins, reported that 53.2% of the infants were born preterm.^31^ Among the 2 studies that reported baseline anthropometry, 1 reported that 12.7% had overweight at age 12 months,^31^ while the other reported that the average weight was 11.6 kilograms at age 18 months.^30^

##### Exposures and comparators

All studies assessed amount or frequency of vegetable consumption up to 24 months,^1,6,27,29–3^,^1^ none of which specified the types of vegetables that were included. Most studies analyzed a continuous measure of the amount or frequency of vegetable consumption,^1,6,29–31^ except for 1 study that compared vegetable consumption greater than, to less than or equal to, the median frequency.^27^ The studies used a variety of assessment methods to measure vegetable consumption. Three studies used a FFQ,^1,27,3^,^1^ 1 study used a 3-day weighed food record,^29,30^ and 1 study used a 24-hour recall.^6^ Three of the studies assessed vegetable consumption multiple times up to age 24 months,^1,6,27^ with 3 studies assessing vegetable consumption up to 12 months,^1,6,27^ and 3 studies assessing vegetable intake beyond 12 months up to 24 months.^1,27,29–31^

##### Outcomes

Four studies examined growth,^6,27,29–31^ 2 studies examined body composition,^30,31^ and 1 study examined risk of overweight.^1^ The outcomes were measured by trained personnel in all studies. The most common outcome measure was BMIZ or BMI (including trajectories or measures of change), which were assessed in all 4 studies. Other outcomes examined included weight and length increment,^31^ WAZ,^31^ HAZ,^31^ waist circumference,^30^ body fat mass and percentage,^31^ and the odds of having a WLZ greater than or equal to 1.1 BMIZ were based on WHO growth standards^27^ and the CDC growth charts.^6,29^ The age at outcome assessment ranged from age 11 months^1^ to 11.5 years.^29^

#### Synthesis of the evidence

All 4 studies that examined growth reported exclusively or predominantly null associations with vegetable consumption across a variety of outcomes from birth to 11.5 years (Table 36).^6,27,29–31^ Among the null associations, the effect sizes were relatively small with mixed directionality. Only 1 study detected a statistically significant association between vegetable consumption and growth, reporting that greater frequency of vegetable consumption at age 18 months was associated with lower BMIZ at age 36 months.^27^

Few studies examined body composition^30,31^ or the risk of obesity,^1,30,31^ all of which reported null associations with vegetable consumption. These studies reported relatively small effect sizes with mixed directions of association.

#### Conclusion statements and grades

The Committee developed a conclusion statement about the relationship between vegetable consumption and growth based on their review of the body of evidence (Table 35). The grade reflects the strength of the evidence underlying the conclusion statement. However, the Committee did not draw a conclusion statement about the relationship between vegetable consumption and body composition and risk of obesity because there is not enough available evidence (Table 35). The risk of bias assessments for the studies that addressed this question are documented in Table 37.

Table 35 Conclusion statements, grades for vegetable consumption by infants and young children and growth, and vegetable consumption by infants and young children and body composition and risk of obesity

Conclusion Statement | Vegetable consumption by infants and young children, up to age 24 months, is not associated with unfavorable outcomes related to growth patterns during childhood. This conclusion is based on evidence graded as limited.
Grade | Limited
Body of Evidence | 5 articles (4 studies): 4 prospective cohort studies
Consistency | Minimal concerns with consistency.
Precision | Some concerns due to few included studies; power calculations were not reported.
Risk of bias | Substantial concerns with risk of bias, particularly due to confounding and missing data.
Directness | Minimal concerns with directness.
Generalizability | Some concerns with applicability to the U.S. population due to few studies being conducted in the United States.
Conclusion Statement | A conclusion statement cannot be drawn about the relationship between vegetable consumption by infants and young children, up to age 24 months, and body composition and risk of obesity during childhood because there is not enough evidence available.
Grade | Grade Not Assignable
Body of Evidence | 3 articles: 3 prospective cohort studies
Rationale | There is not enough evidence available to answer this question.

#### Assessment of the evidence

The body of evidence underlying the graded conclusion statement above includes 5 articles from 4 PCS. The evidence was graded based on an assessment of 5 grading elements, as described below. Publication bias was also a consideration; however, this was not assessed as a serious concern because the body of evidence included studies that reported only nonsignificant findings as well as studies that reported a mix of both significant and nonsignificant results, across a range of analytic sample sizes. However, while the literature search was comprehensive, a search of the gray literature was not done, which could increase the possibility of publication bias.

##### Consistency

Studies consistently reported null associations between vegetable consumption by infants and young children and growth. The studies also examined relatively consistent exposures and outcomes assessed.

##### Precision

Few studies (4) were included that examined consumption of vegetable by infants and young children and growth-related outcomes. The analytic sample sizes ranged from 302 to 1,872. No studies reported a power calculation.

##### Risk of bias

There were several risk of bias concerns across the body of evidence (Table 37). Most of the studies had high risk of bias due to confounding due to studies not accounting for most of the key confounders. One study had a very high risk of bias due to confounding due to a lack of any model adjustments. Most studies had some concerns or high risk of bias due to missing data because of high rates of missing data which was not accounted for. Finally, all studies had some concerns or high risk of bias due to selection of the reported result because none reported a pre-registered protocol or analysis plan.

##### Directness

The studies examined exposures and outcomes that aligned with the analytic framework.

##### Generalizability

There were some concerns with generalizability to the U.S. population due to few studies being conducted in the United States.

Table 36 Evidence examining the relationship between vegetable consumption and growth, body composition, and risk of obesity ^a^

Study and Participant Characteristics | Exposure, Comparator, and Outcome | Results | Key Confounders, Model Adjustments, Funding
Amaro-Rivera, 2019 (https://pubmed.ncbi.nlm.nih.gov/31260549/)^1^; PCS, U.S. (Puerto Rico); [underlined: Analytic N] = 68 (Excluded participants lost to follow-up); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race/ethnicity:] Hispanic: 100%; [underlined: Maternal education:] ≤HS: 32.5%, >HS: 67.5%; [underlined: Other SEP measure(s):] WIC participation: 100%; [underlined: Maternal age:] Parent’s age: <30 y: 55.8%, ≥30 y: 44.2%; [underlined: Milk feeding practices:] EBF for ≥1 mo: 51%, Ever FF: 70.1%, Any BF at ~10 mo: 20.8%; [underlined: Child sex (female):] 47%; [underlined: Birth size:] NR; [underlined: Gestational age:] NR | [underlined: Exposure(s) and comparator(s):] Annual change in vegetables Diet Quality Index Scores (amount; continuous); [underlined: Dietary assessment methods:] Interviewer-administered questionnaire completed by caregivers. Diet Quality Index Score based on FFQ.; [underlined: Age(s) at dietary assessment:] 0–5, 8–36 mo; [underlined: Amounts consumed:] NR; [underlined: Outcome(s):] WLZ (≥1); [underlined: Outcome assessment methods:] Weight and length measured by trained research staff.; Weight status assessed using WHO age- and sex-specific WLZ growth charts. Relative risk for WLZ (≥1 z-score vs <1 z-score), with underweight defined as WLZ ≤-2 SD, healthy weight status defined as WLZ >-2 and <1 SD, risk of overweight defined as WLZ between 1-<2, and overweight or obesity defined as WLZ ≥2 SD.; [underlined: Age(s) at outcome assessment:] 11–36 mo (Median: 21 mo, 11–23 mo: 61.0%, 24–36 mo: 39.0%) | [underlined: WLZ (≥1 vs <1) @ 11–36 mo (RR (95% CI))]; Vegetables score: 0.80 (0.63, 1.02) | [underlined: Key confounders accounted for:] SEP; sex; race and/or ethnicity; milk feeding practices; baseline anthropometry; [underlined: Key confounders NOT accounted for:] gestational age; [underlined: Model adjustments:] WLZ at baseline; [underlined: Funding:] University of Puerto Rico Central Administration Grant; Capacity Advancement in Research Infrastructure; NIMHD
Au, 2023 (https://pubmed.ncbi.nlm.nih.gov/36806452/)^6^; PCS, WIC ITFPS-2, U.S.; [underlined: Analytic N] = 1,523 (24 mo), 1,680 (36 mo), 1,872 (48 mo) (Excluded participants with missing data on HEI-2015 or BMI at 2, 3, or 4 y, born prematurely, had very low birth weight, or had long-term medical problems that could affect eating.); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race/ethnicity:] Hispanic: 40.6%, Non-Hispanic White: 29.1%, Non-Hispanic African American: 24.8%, Non-Hispanic Other: 5.5%; [underlined: Maternal education:] <HS: 24.4%, HS: 37.7%, >HS: 37.5%; [underlined: Other SEP measure(s):] Participating in WIC: 100%; Maternal employment at 6 mo: Full-time: 21.5%, Part-time: 20.2%, Not working for pay: 58.2%; Poverty level at enrollment: ≤75% of poverty guideline: 64.0%, >75-<130%: 26.3%, >130% poverty: 9.7%; [underlined: Maternal age:] 16–19 y: 11.7%, 20–25 y: 41.1%, ≥26 y: 47.3%; [underlined: Milk feeding practices:] Any BF: 81.9%; Any formula use: 95.5%; [underlined: Child sex (female):] 49%; [underlined: Birth weight:] Low (<2.5 kg): 5.3%, Normal (2.5-≤4.5 kg): 93.4%, High (>4.5 kg): 1.3%; [underlined: Gestational age:] Excluded infants born prematurely | [underlined: Exposure(s) and comparator(s):] Vegetables (frequency, continuous, Infant Diet Quality Index component score from 0–1 based on degree of adherence to guidelines; max score: ≥2x/d at 9 mo); [underlined: Dietary assessment methods:] 24-h dietary recall via telephone interview with caregiver; [underlined: Age(s) at dietary assessment:] 1, 3, 5, 7, 9 11, 13, 15, 18, 24, 30, 36, 42, and 48 mo; [underlined: Amounts consumed:] ≥2x/d at 9 mo: 37.0%, None at 9 mo: 22.8%; [underlined: Outcome(s):] BMIZ; [underlined: Outcome assessment methods:] Weight and length/height collected at WIC sites or from child's health care provider. BMIZ based on CDC age- and sex-specific growth charts; [underlined: Age(s) at outcome assessment:] 2, 3, 4 y | [underlined: BMIZ @ 2, 3, 4 y]; 2 y: Data NR, p>0.10; 3 y: Data NR, p>0.10; 4 y: Data NR, p>0.10 | [underlined: Key confounders accounted for:] SEP; sex; gestational age; [underlined: Key confounders NOT accounted for:] race and/or ethnicity; milk feeding practices; baseline anthropometry; [underlined: Model adjustments:] None; [underlined: Funding:] NHLBI; USDA/NIFA
Garden, 2011 (https://pubmed.ncbi.nlm.nih.gov/21346718/)^30^; PCS, CAPS, Australia; [underlined: Analytic N] = 362 (Excluded participants with missing data on diet or anthropometrics); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race/ethnicity:] Grandparents ethnicity/country of birth: Caucasian: 55%, European: 9%, Middle Eastern: 4%, Indian: 5%, Asian: 4%, Undefined: 24%; [underlined: Maternal education:] NR; [underlined: Other SEP measure(s):] Paternal education: ≤10 y: 33%, 11–12 y: 18%, Tertiary education: 48%; [underlined: Maternal age:] NR; [underlined: Milk feeding practices:] BF ≥6 mo: 42%; [underlined: Child sex (female):] 49%; [underlined: Birth weight:] 3,493 (492) g; [underlined: Gestational age:] NR; [underlined: Other relevant characteristics:] Secondary analysis of RCT (testing intervention of house dust mite avoidance and omega-3 supplementation); all children recruited at increased risk of developing asthma | [underlined: Exposure(s) and comparator(s):] Vegetables (amount, continuous, as quintiles); [underlined: Dietary assessment methods:] 3-d weighed food records; [underlined: Age(s) at dietary assessment:] 18 mo; [underlined: Amounts consumed:] Quintiles of vegetable intake; g: 0, 20, 35, 54, 82; % total energy: 0, 1, 3, 5, 7; [underlined: Outcome(s):] BMI, waist circumference; [underlined: Outcome assessment methods:] Weight, length, and waist circumference measured by study nurses; [underlined: Age(s) at outcome assessment:] 8 y | [underlined: BMI @ 8 y (Coefficient (95% CI))]; Vegetables, per quintile; g: 0.20 (0.00, 0.40), p for trend=0.05; % of total energy: 0.13 (−0.06, 0.33), p for trend=0.19; [underlined: WC @ 8 y (Coefficient (95% CI))]; Vegetables, per quintile; g: 0.50 (−0.04, 1.04), p for trend=0.07; % of total energy: 0.29 (−0.25, 0.83), p for trend=0.29 | [underlined: Key confounders accounted for:] SEP; sex; race and/or ethnicity; milk feeding practices; gestational age; [underlined: Key confounders NOT accounted for:] baseline anthropometry; [underlined: Model adjustments:] sex, asthma study intervention group, birth weight, breastfeeding for at least 6 mo, parental obesity status, ethnicity, smoking in pregnancy and father’s education, total energy intake (food intake in g only); [underlined: Funding:] The National Health and Medical Research Council of Australia; Cooperative Research Centre for Asthma; New South Wales Department of Health; Children’s Hospital Westmead; University of Sydney, Faculty of Medicine; Commonwealth Department of Health and Aging
Garden, 2012 (https://pubmed.ncbi.nlm.nih.gov/23201761/)^29^; PCS, CAPS, Australia; [underlined: Analytic N] = 298 (Excluded participants who were not still participating in the study at 11.5 y or did not have dietary data.); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race/ethnicity:] NR (Australian born mother 74%, Australian born father: 69%; Child's grandparents ethnicity/country of birth: Caucasian: ~54%, European: ~9%, Middle Eastern/Indian/Asian: ~12%, Undefined: ~25%); [underlined: Maternal education:] 52% tertiary educated; [underlined: Other SEP measure(s):] Full-time employment: Mother: 49%, Father: 87%; [underlined: Maternal age:] 29.0 (5.1) y; [underlined: Milk feeding practices:] BF duration: 0 to <3 mo: 40%, 3 to <6 mo: 16.8%, ≥6 mo: 43.2%; [underlined: Child sex (female):] 49%; [underlined: Birth weight:] 100% ≥2.5 kg; [underlined: Gestational age:] 100% ≥36 wk; [underlined: Other relevant characteristics:] Secondary analysis of RCT (testing intervention of house dust mite avoidance and omega-3 supplementation); all children recruited at increased risk of developing asthma | [underlined: Exposure(s) and comparator(s):] Vegetables (amount, continuous); [underlined: Dietary assessment methods:] Parent/caregiver completed 3-d weighed food record (2 weekdays and 1 weekend day); [underlined: Age(s) at dietary assessment:] 18 mo; [underlined: Amounts consumed:] See results for intake data; [underlined: Outcome(s):] BMI trajectory; [underlined: Outcome assessment methods:] Weight and height measured by study nurses. Three BMI trajectories defined using latent basis growth mixture model in relationship to CDC percentiles, stratified by sex.; [underlined: Age(s) at outcome assessment:] 1, 3, 6, 9, 12, 18 mo, 2–5 y (every 6 mo), 8 y, 11.5 y | [underlined: BMI trajectory @ birth-11.5 y (median intake at 18 mo by trajectory group)]; Vegetables; Boys: normal trajectory: 43.2 g, early and persistent trajectory: 57.3 g, late BMI increase: 36.3 g, p=0.49; Girls: normal trajectory: 35.3 g, early and persistent trajectory: 43.3 g, late BMI increase: 43.0 g, p=0.48; Results analyzed by % of total energy were similar. | [underlined: Key confounders accounted for:] SEP; sex; race and/or ethnicity; milk feeding practices; baseline anthropometry (multinomial regression only); [underlined: Key confounders NOT accounted for:] gestational age; [underlined: Model adjustments:] dietary intervention group, BF, parental obesity, ethnicity, smoking during pregnancy, father's education status (multinomial regression only); [underlined: Funding:] National Health and Medical Research Council of Australia
Jin, 2022 (https://pubmed.ncbi.nlm.nih.gov/34412548/)^31^; PCS, LoTiS, China; [underlined: Analytic N] = 302 (Excluded participants lost to follow-up); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race/ethnicity:] NR; [underlined: Maternal education:] NR; [underlined: Other SEP measure(s):] NR; [underlined: Maternal age:] 30.47 (3.70) y; [underlined: Milk feeding practices:] BF duration: 7.60 (3.99) mo; Milk feeding at 12 mo: EBF: 4.6%, Exclusive FF: 73.7%, Mixed BF and FF: 21.7%; [underlined: Child sex (female):] 45%; [underlined: Birth weight:] 2.49 (0.45) kg; [underlined: Birth length:] 46.04 (2.40) cm; [underlined: SGA at birth:] 12.4%; [underlined: Gestational age:] 36.43 (1.48) wk; 53.2% born preterm; [underlined: Other relevant characteristics:] 100% twins (both included in analyses) | [underlined: Exposure(s) and comparator(s):] Tubers, Vegetables (frequency, continuous); [underlined: Dietary assessment methods:] FFQ completed by mother/guardian; [underlined: Age(s) at dietary assessment:] 12 mo; [underlined: Amounts consumed:] NR; [underlined: Outcome(s):] WAZ, HAZ, LAZ, BMIZ, percent body fat mass, weight increment (12–24 mo), length increment (12–24 mo), BMI increment (12–24 mo); [underlined: Outcome assessment methods:] Weight and height were measured by study personnel. Body fat was measured using bioimpedance.; [underlined: Age(s) at outcome assessment:] 12, 24 mo | [underlined: WAZ @ 24 mo (spearman correlation)]; Tubers: 0.080, p=0.168; Vegetables: 0.036, p=0.534; [underlined: HAZ @ 24 mo (spearman correlation)]; Tubers: 0.036, p=0.535; Vegetables: 0.036, p=0.534; [underlined: BMIZ @ 24 mo (spearman correlation)]; Tubers: 0.083, p=0.152; Vegetables: –0.031, p=0.587; [underlined: Weight increment from 12 to 24 mo (spearman correlation)]; Tubers: –0.094, p=0.103; Vegetables: –0.008, p=0.889; [underlined: Length increment from 12 to 24 mo (spearman correlation)]; Tubers: 0.000, p=1.000; Vegetables: –0.078, p=0.175; [underlined: BMI increment from 12 to 24 mo (spearman correlation)]; Tubers: –0.037, p=0.543; Vegetables: 0.041, p=0.505; [underlined: Body fat mass @ 24 mo (statistical measure NR, general linear model)]; Tubers: –0.039, p=0.624; Vegetables: –0.078, p=0.327; [underlined: Body fat percentage @ 24 mo (statistical measure NR, general linear model)]; Tubers: –0.069, p=0.388; Vegetables: –0.103, p=0.195 | [underlined: Key confounders accounted for:] sex; baseline anthropometry (growth increments only); [underlined: Key confounders NOT accounted for:] SEP; race and/or ethnicity; milk feeding practices; gestational age; baseline anthropometry (WAZ, HAZ, BMIZ, body fat mass, body fat percentage); [underlined: Model adjustments:] sex (body fat mass, % body fat mass); None (all other outcomes); [underlined: Funding:] National Key Research and Development Program of China; National Natural Science Foundation of China; Chongqing Joint Program of Science and Health; Key Disciplines of Medical and Health Research of Yuhang District of Hangzhou City
Mahoney, 2018 (https://pubmed.ncbi.nlm.nih.gov/29607793/)^27^; PCS, Born in Bradford 1000, U.K.; [underlined: Analytic N] = 12 mo: 722; 18 mo: 779 (Excluded participants with multiple births, missing child dietary data or outcome data, and not of White British or Pakistani ethnicity); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race/ethnicity:] Pakistani: ~56%, White British: ~44%; [underlined: Maternal education:] NR; [underlined: Other SEP measure(s):] NR; [underlined: Maternal age:] NR; [underlined: Milk feeding practices:] NR; [underlined: Child sex (female):] NR; [underlined: Birth weight:] 3,234.15 (521.97) g; [underlined: Gestational age:] NR | [underlined: Exposure(s) and comparator(s):] Vegetables (frequency, ≤ vs > Median); [underlined: Dietary assessment methods:] FFQ completed by parents; [underlined: Age(s) at dietary assessment:] 12, 18 mo; Amounts consumed: Frequency at 12, 18 mo, respectively (Median, IQR): Vegetables per d: 1.7 (1.1, 2.6) x/wk, 6.0 (4.0, 6.0) x/wk; [underlined: Outcome(s):] BMIZ; [underlined: Outcome assessment methods:] Height, weight measured by trained researchers. Age- and sex-adjusted BMI calculated based on WHO 2006 standards.; [underlined: Age(s) at outcome assessment:] 36 mo | [underlined: BMIZ @ 36 mo (β (95% CI))]; Intake @ 12 mo: > vs ≤ 1.7x/d: −0.06 (−0.21, 0.10), p=0.48; Intake @ 18 mo: > vs ≤ 6.0x/d: −0.20 (−0.36, −0.03), p=0.02 | [underlined: Key confounders accounted for:] Sex; race and/or ethnicity; [underlined: Key confounders NOT accounted for:] SEP; milk feeding practices; gestational age; baseline anthropometry; [underlined: Model adjustments:] Ethnicity, sex, birth weight, other key indicator food groups (formula milk; commercial savoury baby foods; commercial sweet baby foods; chips, roast and potato shapes; processed meat products; vegetables; fruit; cakes, biscuits, chocolate and sweets; crisps and savoury snacks; sugar-sweetened drinks; pure fruit juice; low-sugar drinks; water); [underlined: Funding:] NIHR

a Abbreviations: @: at; β: beta; BF: breastfeeding; BMI: body mass index; BMIZ: BMI z-score; CAPS: Childhood Asthma Prevention Study; CDC: Centers for Disease Control and Prevention; CI: confidence interval; cm: centimeter; d: day; EBF: exclusive breastfeeding; FF: formula feeding; FFQ: food frequency questionnaire; g: gram; HAZ: height for age z-score; HEI: Healthy Eating Index; HS: high school; IQR: interquartile range; LAZ: length for age z-score; LoTiS: Longitudinal Twin Study; mo: month; NR: not reported; OR: odds ratio; PCS: prospective cohort study; RCT: randomized controlled trial; ref: reference; RR: risk ratio; SD: standard deviation; SEP: socioeconomic position; U.K.: United Kingdom; U.S.: United States; vs: versus; WAZ: weight for age z-score; WHO: World Health Organization; WIC: Special Supplemental Nutrition Program for Women, Infants, and Children; WIC-IFTPS-2: WIC Infant and Toddler Feeding Practices Study-2; wk: week; WLZ: weight for length z-score; x: times; y: year

Table 37 Risk of bias for observational studies examining vegetable consumption and growth, body composition, and risk of obesity ^a^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Amaro-Rivera, 2019^1^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Au, 2023^6^ | HIGH | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Garden, 2011^30^ | SOME CONCERNS | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Garden, 2012^29^ | SOME CONCERNS | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Jin, 2022^31^ (body fat mass, % fat mass) | HIGH | SOME CONCERNS | LOW | LOW | LOW | LOW | HIGH | HIGH
Jin, 2022^31^ (BMIZ, HAZ, WAZ, growth increments) | VERY HIGH | SOME CONCERNS | LOW | LOW | LOW | LOW | HIGH | VERY HIGH
Mahoney, 2018^27^ | HIGH | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH

a Possible ratings of low, some concerns, high, very high, no information, or not applicable determined using the "Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)" tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602. ) *Low risk of bias except for concerns about uncontrolled confounding.

### Grains

#### Description of the evidence

Nine studies (from 14 articles) met inclusion criteria and examined the relationship between consumption of grains among infants and young children, up to age 24 months, and growth, body composition, and risk of obesity (Table 39).^1,29,30,32–42^ Two studies were randomized controlled trials (RCTs; 1 cluster RCT^39,41^ and 1 parallel RCT35). Seven studies were PCS,^1,29,30,32–34,36–38,40,42^ using data from the following cohorts: CAPS,^29,30^ Halland Health and Growth Study (H2GS),^32,33,37^ IFPS II,^34,42^ NorthPop,^38^ Nurture,^40^ and 2 unnamed cohorts.^1,36^ One study was a prospective analysis of an RCT that aimed to examine the effect of dust mite prevention and omega-3 supplementation on asthma prevention.^29,30^

##### Population

Four studies were conducted in the United States,^1,34,35,40,42^ including 1 study from Puerto Rico,^1^ 2 studies were conducted in Sweden,^32,33,37,38^ and 1 study each was conducted in Australia,^29,30^ China,^39,41^ and Norway.^36^ Two articles from the unnamed cohorts were from the same cohort.^39,41^ The analytic sample sizes of the studies ranged from 681 to 2,404.^32^ Most studies did not report power calculations related to grains consumption and the relevant outcomes.^1,29,30,32–34,36–42^ The 1 study that did report power noted that it was not sufficiently powered.^35^

Five studies provided information on the racial and/or ethnic background of participants: 100% of the participants were Chinese in 1 study^41^; in another, 100% of participants were Hispanic^1^; in the third study, 91% of participants were White, while the remaining participants were Hispanic (5%) and Black (4%)^34^; the fourth study reported that 72% of participants were Black, 19% were White, and 7% were Latina^40^; finally, the fifth study reported that the child’s grandparent’s ethnicity or country of birth 0was Caucasian (54%), European (9%), Middle Eastern/Indian/Asian (12%), and undefined (25%).^29,30^ Average maternal age tended to be in the mid-twenties to early-thirties^29,38,40,42^ or a large proportion of participants were in this age range,^1,32,34,36,37^ across the 7 studies that reported this information.,^1,29,32,34,36–38,40,42^ Human milk and formula feeding practices were reported in 8 studies and were varied.^1,29,30,32–37,39–42^ Among the RCTs, all infants were exclusively breastfed at enrollment (ranging from approximately age 4 to 6 months).^35,39,4^,^1^ Among the 3 PCS that reported on exclusive breastfeeding, 51% were exclusively breastfeeding at 1 month in 1 study,^1^ 46% were exclusively breastfeeding at 4 months in the second study,^36^ while the third study reported that 2% of participants were exclusively breastfeeding at 6 months.^32^ Duration of any breastfeeding also tended to vary across studies: 1 study reported that 79%,^32^ 58%,^32^ and 5–9%^33,37^ of participants were breastfeeding at 4, 6, and 12 months, respectively, a second study reported that 42% of participants were breastfeeding at 6 months,^30^ a third reported that 21% were breastfeeding at 10 months,^1^ while a fourth study reported that the mean duration of breastfeeding was 14.7 weeks.^40^ One study reported breastfeeding intensity, noting that ≥20% of milk feedings were breast milk at age 2 months for 67% of participants.^34^

Measures of SEP were reported in 8 studies.^1,29,32–34,36–38,40–42^ Maternal education was reported across 8 studies, with most noting that 50% of the participants, or more, had at least 12 years or a high school level of education^1,29,32–34,36–38,40,42^ although in 1 study approximately 55% had at least 9 years of education.41 Among the 3 studies that reported household income,^34,38,40^ 1 study reported that 61% had a household income less than or equal to 349% of federal poverty line,^34^ 74% had a household income of $40,000 or less in a second study,^40^ and the final study reported an average household disposable income of 526,058 Swedish Krona.^38^ One study exclusively enrolled participants who were participating in WIC,^1^ while a second study reported that 38% of participants participated in WIC.^42^

Regarding the characteristics of the infants and young children, approximately 50% of participants were female^1,29,30,33–40,42^ and mean birth weight ranged from approximately 3.4^35^ to 3.8^36^ kilograms. Of the 8 studies that reported gestational age, 6 studies exclusively enrolled full-term infants,^35–4^,^1^ while 1 study exclusively enrolled infants born at or after 36 weeks^29^ and a second study reported a mean gestational age of approximately 39 weeks.^42^ Baseline anthropometry was reported in 5 studies.^30,33,35,37,39–41^ Across both RCTs, there were no significant differences between groups in baseline anthropometry.^35,39,41^ The remaining 3 studies reported 24% had high infant weight gain during the first year in 1 study,^33^ mean weight and length at age 18 months was 11.6 kilograms and 83.4 cm, respectively, in the second study^30^ and WLZ at age 3 months was 0.14 in the third study.^40^

##### Exposures and comparators

The 2 RCTs compared the effect of consuming infant cereal, fortified^35,39,41^ or unfortified,^39,41^ to consuming meat.^35,39,41^ The intervention period was from age 6 to 18 months in 1 study^39,41^ and from approximately age 4–6 to 7 months in the other.^35^ A variety of exposures were examined across the PCS. Two studies examined the frequency or amount of milk cereal drink consumption,^32,33,37,38^ 2 studies examined porridge,^32,33,36^ and 1 study each examined infant cereal added to bottles,^34,42^ cereal foods (i.e., bread, pasta, rice, breakfast cereals),^29,30^ cereal-based foods (i.e., cookies, crackers, doughnuts, cakes, pies, buns, muffins, pizza),^29,30^ whole grains,^1^ refined grains,^1^ and baby snacks (teething biscuits, puffs, melts).^40^ Four studies analyzed the exposures continuously,^1,29,30,36,42^while the remaining studies examined the exposures categorically. ^32–34,37,38,40^

The PCS used a variety of assessment methods to measure dietary intake, including FFQs,^1,36,38,42^ 3 studies other questionnaires,^32,34,37,40^ and 3-day food records.^29,30,35^ The assessments were conducted across a wide range of ages, spanning from age 1 months up to age 24 months, with 6 measuring consumption up to age 12 months^1,32–34,36–38,40,42^ and 3 measuring consumption after age 12 months.^1,29,30,33^ Four studies conducted multiple assessments of grains consumption between birth and age 24 months.^1,33,40,42^

##### Outcomes

Eight studies examined measures of growth,^29,30,34–37,39–42^while 1 study assessed body composition,^30^ and 3 studies examined the risk of overweight or obesity.^1,32,33,38^ A variety of outcome measures were reported across the studies including BMI,^30,36^ BMIZ,^29,38^ WLZ,^39–41^ WAZ,^39,41^ LAZ,^39,41^ weight,^34,35^ rapid infant weight gain,^37,42^ length,^35,41^ head circumference,^35,41^ waist circumference,^30^ and risk of overweight or obesity, based on a variety of cut-offs.^1,32,33,38^ Five of the studies examined change or trajectories of the outcomes over time,^29,34,35,37,41,42^ while 6 studies examined outcomes measured at single time points.^1,30,32,33,36,38–40^ Research staff or nurses measured the outcomes in all but 1 study, which collected maternal report of infant weight at the last doctor’s visit.^34,42^ The ages at which the outcomes were measured ranged from age 6 months^40^ up to age 11.5 years.^29^

#### Synthesis of the evidence

Across both RCTs and PCS, most studies reported predominantly or exclusively null effects or associations of grains with measures of growth and risk of overweight or obesity, although 5 studies did report some significant relationships with grains consumption (Table 39).^35,39,41^

Regarding the null findings, the 2 RCTs^35,39,41^ reported null effects comparing consumption of meat to infant cereal on outcomes predominantly related to weight from age 7 to 18 months. However, 1 of these RCT is less generalizable to the U.S. population as it was conducted in an area of China with moderate stunting levels.^39,41^ Across the PCS, 6 studies did not detect significant associations between a variety of grain products,^1,36–38,40^ including infant porridge,^32,33,36^ milk cereal drink,^37,38^ baby snacks,^40^ whole grains,^1^ and refined grains,^1^ and outcomes related to growth, such as BMIZ and WLZ, and risk of overweight or obesity from infancy through early childhood. Across the 7 studies that reported any null associations, studies tended to show a nonsignificant positive association between baby snacks,^40^ cereal foods,^30^ cereal added to bottle,^34^ whole grains,^1^ refined grains,^1^ and milk cereal drink^33^ and outcomes related to growth and risk of overweight or obesity.

Half of these studies also reported significant effects or associations of grains with measures of growth and risk of overweight or obesity. Both of the RCTs reported that infants fed cereal had significantly lower non-weightrelated growth, including length^39,41^ and head circumference,^35^ compared to infants fed meat. Three of the 8 PCS also reported significant associations,^30,32–34,42^ all of which varied in the type of grains examined, including milk cereal drink,^32,33^ cereal-based foods,^30^ and cereal added to baby bottle.^34,42^ The directionality of these studies were mixed, with 2 studies reporting a tendency for rapid weight gain or risk of overweight with cereal added to bottle and milk cereal drink, respectively, and 1 study reporting lower BMI with greater cereal-based foods consumption.

The single study that assessed body composition reported mixed findings: consumption of cereal foods, which included bread, pasta, rice, and breakfast cereals, at age 18 months was not associated with waist circumference, while greater consumption of cereal-based foods, which included cookies, crackers, doughnuts, cakes, pies, buns, muffins, and pizza, was associated with lower waist circumference at age 8 years (Table 39).^30^

#### Conclusion statements and grades

The Committee developed a conclusion statement about the relationship between grains consumption and growth and risk of obesity based on their review of the body of evidence (Table 38). The grade reflects the strength of the evidence underlying the conclusion statement. However, the Committee did not draw a conclusion statement about the relationship between grains consumption and body composition because there is not enough available evidence (Table 38). The risk of bias assessments for the studies that addressed this question are documented in Table 40, Table 41, and Table 42 for parallel RCTs, cluster-RCTs, and PCS, respectively.

Table 38 Conclusion statement, grade for grains consumption by infants and young children and growth and risk of obesity

Conclusion Statement | Grains consumption by infants and young children, from age 6 months up to age 24 months, is not associated with unfavorable outcomes related to growth patterns and risk of obesity during childhood. This conclusion is based on evidence graded as limited.
Grade | Limited
Body of Evidence | 14 articles (9 studies): 2 randomized controlled trials (3 articles), 7 prospective cohort studies (11 articles)
Consistency | Some concerns due to some inconsistency in the results, as well as the exposures examined.
Precision | Substantial concerns due to insufficient power or lack of information on power.
Risk of bias | Substantial concerns, particularly due to randomization in randomized controlled trials, and confounding, exposure measurement, and missing data in observational studies.
Directness | Some concerns due to some studies that were less direct.
Generalizability | Some concerns due to most studies conducted outside the United States and some studies examining exposures less generalizable to the United States.
Conclusion Statement | A conclusion statement cannot be drawn about the relationship between grains consumption by infants and young children, from age 6 months up to age 24 months, and outcomes related to body composition during childhood because there is not enough evidence available.
Grade | Grade Not Assignable
Body of Evidence | 1 article: 1 prospective cohort study
Rationale | There is not enough evidence available to answer this question.

#### Assessment of the evidence

The body of evidence underlying the graded conclusion statement above includes 14 articles from 2 RCT and 7 PCS. The evidence was graded based on an assessment of 5 grading elements, as described below. Publication bias was also a consideration; however, this was not assessed as a serious concern because the body of evidence included studies that reported only nonsignificant findings as well as studies that reported a mix of both significant and nonsignificant results, across a range of analytic sample sizes. However, while the literature search was comprehensive, a search of the gray literature was not done, which could increase the possibility of publication bias.

##### Consistency

The studies were somewhat inconsistent in regard to both the significance and direction of findings. Specifically, several studies reported null findings, some studies reported a mix of null and significant results for greater growth or risk of overweight or obesity, and some studies reported a mix of null and significant results for lower growth. The studies varied in the grain products that were examined, with some assessing specific products such as infant cereal or milk cereal drink, and others measuring broader categories of products such as whole and refined grains, cereal foods, and cereal-based products.

##### Precision

There were substantial concerns in precision across this body of evidence. One trial reported that they did not have sufficient power. The remaining studies provided no information on power.

##### Risk of bias

There were several risk of bias concerns across the body of evidence (Table 40, Table 41, and Table 42). First, both RCTs had some concerns for or were at high risk of bias due to randomization. Next, across the PCS, all had at least some risk of bias concerns due to confounding because none accounted for every key confounder. Two of these studies had a very high risk of bias due to confounding as no model adjustments were made. Most PCS also had some concerns with risk of bias due to exposure measurement because of the use of unvalidated measures. Most studies had high risk of bias due to missing data because high levels of missing data were present but not accounted for. With the exception of 1 RCT, all studies had some concerns or high risk of bias due to selection of the reported result because pre-registered protocols or analysis plans were not available. Risk of bias due to selection of participants, post-exposure interventions, and outcome measurement were predominantly assessed as low.

##### Directness

The populations, interventions/exposures, comparators, and outcomes examined in the studies were primarily directly related to the systematic review question. One study examined infant cereal provided in a bottle, but this less direct exposure was not weighed heavily in the synthesis.

##### Generalizability

There were some concerns with generalizability to the U.S. population due to less than half of the studies being conducted in the United States. Additionally, several studies examined exposures that are less generalizable to the United States, such as milk cereal drink. However, several studies had representation of individuals across different racial and/or ethnic groups and SEP levels, such as maternal education.

Table 39 Evidence examining the relationship between grains consumption and growth, body composition, and risk of obesity ^a^

Study and Participant Characteristics | Intervention/Exposure, Comparator, and Outcome | Results | Key Confounders, Model Adjustments, Funding
RCT-Parallel
Krebs, 2006 (https://pubmed.ncbi.nlm.nih.gov/16456417/)^35^; RCT-Parallel, U.S.; [underlined: Analytic N by group:] Meat: n=38, Cereal: n=34; [underlined: Attrition:] Meat: 18%, Cereal: 18% (Excluded participants who dropped out due to inability to continue EBF, return to work, relocation); [underlined: Adequately powered:] No; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race/ethnicity:] NR; [underlined: Maternal education:] NR; [underlined: Other SEP measure(s):] NR; [underlined: Maternal age:] NR; [underlined: Milk feeding practices:] 100% EBF at 4 mo; [underlined: Child sex (female):] 51%; [underlined: Birth weight:] ~3.37 kg; [underlined: Gestational age:] 100% born at term | [underlined: Intervention(s):] Meat group: Received pureed beef (Gerber Beef and Beef Gravy, Second Foods) as first complementary food from ~4–6 mo - 7mo; deferred introduction of infant cereal until after 7 mo; encouraged to wait until ~5 months to start complementary food; [underlined: Comparator(s):] Cereal group: Received Fe-fortified cereal from ~4–6 mo - 7mo (Gerber Fe fortified infant rice cereal, without Zn, First Foods) as first complementary food, mixed with either expressed human milk or water on approximately a 1:2 ratio of cereal to fluid; deferred introduction of meats/other high protein foods until after 7 mo; encouraged to wait until ~5 months to start complementary food; [underlined: Dietary assessment methods:] 3-d diet records; [underlined: Compliance:] NR; [underlined: Age at intervention:] ~4–6 mo - 7 mo; [underlined: Intervention duration:] ~2 mo; [underlined: Outcome(s):] Weight, length, HC, weight-for-length; [underlined: Outcome assessment methods:] Weight, length, and head circumference were measured by trained study nurses.; Percentiles for weight-for-length for age based on CDC data.; [underlined: Age(s) at outcome assessment:] 4 mo, 5 mo, 6 mo, 7 mo, 9 mo, 12 mo | [underlined: Monthly weight change (g) from 4–7 mo and 7–12 mo (mean (SE))]; Meat vs Cereal; From 4–7 mo: 399 (20) vs 427 (21), p=NS; From 7–12 mo: 267 (17) vs 252 (18), p=NS; [underlined: Monthly length change (cm) from 4–7 mo and 7–12 mo (mean (SE))]; Meat vs Cereal; From 4–7 mo: 1.62 (0.062) vs 1.78 (0.065), p=NS; From 7–12 mo: 1.25 (0.046) vs 1.27 (0.048), p=NS; [underlined: Monthly HC change (cm) from 4–7 mo and 7–12 mo (mean (SE))]; Meat vs Cereal; From 4–7 mo: 0.79 (0.028) vs 0.81 (0.028), p=NS; From 7–12 mo: 0.48 (0.018) vs 0.41 (0.019), p=0.02; [underlined: Monthly weight-for-length percentile from 4–7 mo and 7–12 mo (mean)]; Meat vs Cereal; At 4–7 mo: Data NR, p=NS At 7–12 mo: Data NR, p=NS | [underlined: Model adjustments:] Birth weight, gestational age, sex; [underlined: Funding:] National Cattleman's Beef Association, NIH, Gerber Products Company (food provision)
RCT-Cluster
Ma, 2016 (https://pubmed.ncbi.nlm.nih.gov/27923057/)^39^; RCT-Cluster, China; [underlined: Analytic N by group:] Meat: n=137 (20 clusters); Fortified cereal: n=140 (20 clusters); Local cereal: n=133 (20 clusters); [underlined: Attrition:] NA for sub-samples (attrition before sub-sample identified: Meat: 10%, Fortified cereal: 10%, Local cereal: 14%) (Excluded participants who were lost to follow-up or who were not randomly selected for the sub-sample for blood collection and analysis.); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race/ethnicity:] NR; [underlined: Maternal education:] NR; [underlined: Other SEP measure(s):] NR; [underlined: Maternal age:] NR; [underlined: Milk feeding practices:] 100% EBF at enrollment (5 mo); [underlined: Child sex (female):] 48%; [underlined: Birth weight:] 100% >2,000 g; [underlined: Gestational age:] 100% with term delivery (37–42 wk) | [underlined: Intervention(s):] Meat: Minced fresh, certified safe pork to be boiled and served daily (50 g); [underlined: Comparator(s):] Fortified cereal: Commercially available fortified cereal (Fe, Zn, vitamin B12); Local cereal: isocaloric local cereal (made of glutinous rice flour, white granulated sugar, and honey).; [underlined: Dietary assessment methods:] Consumption checked and recorded by community doctors biweekly (meat) or weekly (cereal); [underlined: Compliance:] NR; [underlined: Age at intervention:] 6 mo to 18 mo; [underlined: Intervention duration:] 12 mo; [underlined: Outcome(s):] LAZ, WAZ, WLZ; [underlined: Outcome assessment methods:] Length and weight measured by trained study personnel. Z scores calculated using 2006 WHO Child Growth Standards; [underlined: Age(s) at outcome assessment:] 6, 12, and 18 mo | [underlined: LAZ @ 18 mo (mean (SD))]; Meat vs Fortified cereal vs Local cereal; −1.47 (0.99) vs −1.83 (0.95) vs −1.67 (0.97), p=0.024; (Meat vs Fortified cereal, p<0.05); [underlined: Change in LAZ from 6 to 18 mo (mean (SD))]; Meat vs Fortified cereal vs Local cereal; −0.41 (0.78) vs −0.71 (0.64) vs −0.62 (0.75), p=0.021; (Meat vs Local cereal and Meat vs Fortified cereal, p<0.05); [underlined: WAZ @ 18 mo (mean (SD))]; Meat vs Fortified cereal vs Local cereal; −0.89 (0.93) vs −1.04 (0.89) vs −0.91 (0.88), p=0.496; [underlined: Change in WAZ @ 6–18 mo (mean (SD))]; Meat vs Fortified cereal vs Local cereal; −0.42 (0.61) vs −0.43 (0.58) vs −0.34 (0.73), p=0.872; [underlined: WLZ @ 18 mo (mean (SD))]; Meat vs Fortified cereal vs Local cereal; −0.27 (0.92) vs −0.24 (0.84) vs −0.15 (0.82), p=0.507; [underlined: Change in WLZ @ 6–18 mo (mean (SD))]; Meat vs Fortified cereal vs Local cereal; −0.61 (0.90) vs −0.44 (0.78) vs −0.36 (0.86), p=0.114 | [underlined: Model adjustments:] sex, birth weight, mother's pre-pregnancy BMI; [underlined: Funding:] National Natural Science Foundation of China, Thrasher Foundation
Tang, 2014 (https://pubmed.ncbi.nlm.nih.gov/25639137/)^41^; RCT-Cluster, China; [underlined: Analytic N by group:] Meat: n=462 (20 clusters), Cereal: n=856 (40 clusters); [underlined: Attrition:] Meat: 10%; Cereal: 11% (Reasons for attrition NR); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race/ethnicity:] Chinese: 100%; [underlined: Maternal education:] ≥9 y education: ~55%; [underlined: Other SEP measure(s):] Paid work: ~7%; [underlined: Maternal age:] NR; [underlined: Milk feeding practices:] 100% EBF at 6 mo (enrollment); [underlined: Child sex (female):] NR; [underlined: Birth size:] NR; [underlined: Gestational age:] 100% with term delivery | [underlined: Intervention(s):] Meat: Minced fresh, certified safe pork to be boiled and served daily (60 g); [underlined: Comparator(s):] Cereal: Commercially available or isocaloric packaged pressed rice cereal product produced locally; [underlined: Dietary assessment methods:] Weekly histories and observation of feeding; [underlined: Compliance:] NR; [underlined: Age at intervention:] 6 mo to 18 mo; [underlined: Intervention duration:] 12 mo; [underlined: Outcome(s):] Length, weight, HC, LAZ, WAZ, WLZ, HCZ; [underlined: Outcome assessment methods:] Length, weight, and HC measured by trained study personnel. Z scores calculated using WHO standards.; [underlined: Age(s) at outcome assessment:] 6, 7, 9, 12, 15, and 18 mo | [underlined: Change in length (cm) from 6 to 18 mo (mean (SD))]; Meat vs Cereal: 13.01 (1.9) vs 12.75 (1.8), p=0.01; [underlined: Change in LAZ from 6 to 18 mo (mean (SD))]; Meat vs Cereal:−0.43 (0.72) vs −0.54 (0.67), p<0.01; [underlined: Change in weight (kg) from 6 to 18 mo (mean (SD))]; Meat vs Cereal: 2.45 (0.60) vs 2.38 (0.60), p=0.08; [underlined: Change in WAZ from 6 to 18 mo (mean (SD))]; Meat vs Cereal: −0.35 (0.60) vs −0.43 (0.61), p=0.05; [underlined: Change in WLZ from 6 to 18 mo (mean (SD))]; Meat vs Cereal: −0.47 (0.79) vs −0.50 (0.81), p=0.62; [underlined: Change in HC (cm) from 6 to 18 mo (mean (SD))]; Meat vs Cereal: 3.80 (0.73) vs 3.82 (0.65), p=0.66; [underlined: Change in HCZ from 6 to 18 mo (mean (SD))]; Meat vs Cereal: −0.19 (0.56) vs −0.18 (0.50), p=0.87 | [underlined: Model adjustments:] Baseline length, baseline LAZ, maternal education, work status, maternal height and weight; [underlined: Funding:] Thrasher Foundation; Science and Technology Commission of Shanghai Municipality; National Natural Science Foundation of China; Shanghai Key Laboratory of Pediatric Gastroenterology and Nutrition; NIH
PCS
Almquist-Tangen, 2013 (https://pubmed.ncbi.nlm.nih.gov/24028671/)^32^; PCS, H2GS, Sweden; [underlined: Analytic N] = 2,404 (12 mo), 2,241 (18 mo) (Excluded participants lost to follow-up); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race/ethnicity:] NR; [underlined: Maternal education:] <12 y: 46%, >13 y: 54%; [underlined: Other SEP measure(s):] Paternal education: <12 y: 62%, >13 y: 38%; [underlined: Maternal age:] <25 y: 10%, 25–34 y: 67%, ≥35 y: 23%; [underlined: Milk feeding practices:] BF at 4 mo: 78.7%, EBF at 4 mo: 74.4%, Mixed feeders at 4 mo: 4.3%, exclusively FF at 4 mo: 21.3%; BF at 6 mo: 58.3%, EBF at 6 mo: 1.6%; [underlined: Child sex (female):] NR; [underlined: Birth size:] NR; [underlined: Gestational age:] NR | [underlined: Exposure(s) and comparator(s):] Milk cereal drink (gruel made from flour boiled in water, consumed from a bottle) at 6 mo (yes vs no (ref)); Porridge at 6 mo (yes vs no (ref)); [underlined: Dietary assessment methods:] Family questionnaire; [underlined: Age(s) at dietary assessment:] 6 mo; [underlined: Amounts consumed:] Milk cereal drink at 6 mo: 46.6% (Of these, 1–2 250 mL; bottles/d: 59.8%, 3–4 bottles/d: 25%, 5–6; bottles/d: 14%); Porridge at 6 mo: 87.7%; [underlined: Outcome(s):] High BMI (BMI >1 SD in study population); [underlined: Outcome assessment methods:] Height and weight measured by trained child health nurses; [underlined: Age(s) at outcome assessment:] 12 mo, 18 mo | [underlined: High BMI (>1 SD) @ 12 mo, 18 mo (OR (95% CI))]; Milk cereal drink at 6 mo: yes vs no (ref); 12 mo: 1.66 (1.07, 2.57), p=0.02; 18 mo: 1.58 (1.04, 2.39), p=0.03; Porridge at 6 mo: yes vs no (ref) 12 mo: 0.79 (0.40, 1.57), p=0.51; 18 mo: 0.73 (0.39, 1.38), p=0.33 | [underlined: Key confounders accounted for:] SEP; sex; milk feeding practices; gestational age; baseline anthropometry; [underlined: Key confounders NOT accounted for:] race and/or ethnicity; [underlined: Model adjustments:] maternal and paternal obesity, maternal and paternal education, maternal smoking, age and sex of infant, birth weight, gestational age, BMI at 4 wk, BMI at 4 mo, BMI at 6 mo; [underlined: Funding:] Research and Development Department, Halland
Almquist-Tangen, 2019 (https://pubmed.ncbi.nlm.nih.gov/30511422/)^32^; PCS, H2GS, Sweden; [underlined: Analytic N] = 1,745 (Excluded participants lost to follow-up); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race/ethnicity:] NR; [underlined: Maternal education:] <9 y: 5%, 9–12 y: 42%, >12 y: 53%; [underlined: Other SEP measure(s):] Paternal education: <9 y: 6%, 9–12 y: 58%, >12 y: 36%; [underlined: Maternal age:] NR; [underlined: Milk feeding practices:] Any BF at 12 mo: 9%; [underlined: Child sex (female):] 51%; [underlined: LGA:] 3%; [underlined: SGA:] 3%; [underlined: Gestational age:] NR | [underlined: Exposure(s) and comparator(s):] Milk cereal drink (Fe-fortified liquid foods made of cereal boiled in milk, commercially available, nutritionally similar to porridge) at 12 mo (3+ bottles/d, 1–2 bottles/d, vs no use (ref)); Milk cereal drink at 6, 12, 18, and 24 mo (yes vs no (ref)); Porridge at 12 mo (yes vs no (ref)); [underlined: Dietary assessment methods:] Parent questionnaires; [underlined: Age(s) at dietary assessment:] 1, 4, 6, 12, 18, 24, 36, 48, and 60 mo; [underlined: Amounts consumed:] Milk cereal drink at 12 mo: 3+ bottles/d: 19%, 1–2 bottles/d: 66%, No use: 15% Porridge at 12 mo: 89%; [underlined: Outcome(s):] Overweight; [underlined: Outcome assessment methods:] Weight and length measured at child health care centers by trained nurses. Overweight defined based on data from 6 nationally representative cross-sectional growth studies (Brazil, Great Britain, Hong Kong, the Netherlands, Singapore, U.S.) using the centile curve that would pass through BMI = 25 at 18 y; [underlined: Age(s) at outcome assessment:] 36, 48, 60 mo | [underlined: Overweight @ 5 y (Crude OR (95% CI))]; Porridge at 12 mo, yes vs no (ref): 1.20 (0.76, 1.88), p=0.43; [underlined: Overweight @ 5 y (OR (95% CI))]; Milk cereal drink at 12 mo; 1–2 bottles/d vs no use (ref), 1.94 (1.08, 3.50), p=0.028; 3+ bottles/d vs no use (ref): 1.11 (0.54, 2.26), p=0.78; [underlined: Overweight @ 36, 48, 60 mo (Crude OR (95% CI))]; Milk cereal drink at 6 mo, yes vs no (ref); 36 mo: 1.35 (1.03, 1.76), p<0.05; 48 mo: 1.42 (1.07, 1.89), p<0.05; 60 mo: 1.13 (0.84, 1.51), p=NS; Milk cereal drink at 12 mo, yes vs no (ref); 36 mo: 1.59 (1.04, 2.44), p<0.05; 48 mo: 1.48 (0.94, 2.30), p=NS; 60 mo: 1.75 (1.08, 2.82), p<0.05; Milk cereal drink at 18 mo, yes vs no (ref) 36 mo: 1.24 (0.87, 1.77), p=NS; 48 mo: 1.07 (0.75, 1.54), p=NS; 60 mo: 1.22 (0.83, 1.81), p=NS; Milk cereal drink at 24 mo, yes vs no (ref) 36 mo: 1.00 (0.74, 1.35), p=NS; 48 mo: 0.93 (0.68, 1.26), p=NS; 60 mo: 0.84 (0.61, 1.16), p=NS | [underlined: Key confounders accounted for:] Milk cereal drink at 12 mo: SEP; sex; milk feeding practices; gestational age; baseline anthropometry; [underlined: Key confounders NOT accounted for:] Porridge at 12 mo, Milk cereal drink at 6, 18, and 24 mo: SEP; sex; race and/or ethnicity; milk feeding practices; gestational age; baseline anthropometry; Milk cereal drink at 12 mo: race and/or ethnicity; [underlined: Model adjustments:] Porridge at 12 mo, Milk cereal drink at 6, 18, and 24 mo: None; Milk cereal drink at 12 mo: Maternal obesity, paternal obesity, maternal education, paternal education, paternal smoking, large for gestational age, sex; [underlined: Funding:] Research and Development Department at the Region of Halland and from Region Skane
Amaro-Rivera, 2019 (https://pubmed.ncbi.nlm.nih.gov/31260549/)^1^; PCS, U.S. (Puerto Rico); [underlined: Analytic N] = 68 (Excluded participants lost to follow-up); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race/ethnicity:] Hispanic: 100%; [underlined: Maternal education:] ≤HS: 32.5%, >HS: 67.5%; [underlined: Other SEP measure(s):] WIC participation: 100%; [underlined: Maternal age:] Parent’s age: <30 y: 55.8%, ≥30 y: 44.2%; [underlined: Milk feeding practices:] EBF for ≥1 mo: 51%, Ever FF: 70.1%, Any BF at ~10 mo: 20.8%; [underlined: Child sex (female):] 47%; [underlined: Birth size:] NR; [underlined: Gestational age:] NR | [underlined: Exposure(s) and comparator(s):] Annual change (amounts) in whole grains, refined grains Diet Quality Index Scores (continuous); [underlined: Dietary assessment methods:] Interviewer-administered questionnaire completed by caregivers. Diet Quality Index Score based on semi-quantitative FFQ.; [underlined: Age(s) at dietary assessment:] 0–5, 8–36 mo (types/amounts); [underlined: Amounts consumed:] NR; [underlined: Outcome(s):] WLZ (≥1); [underlined: Outcome assessment methods:] Weight and length measured by trained research staff. Weight status assessed using WHO age- and sex-specific WLZ growth charts. Relative risk for WLZ (≥1 z-score vs <1 z-score), with underweight defined as WLZ ≤-2 SD, healthy weight status defined as WLZ >-2 and <1 SD, risk of overweight defined as WLZ between 1-<2, and overweight or obesity defined as WLZ ≥2 SD.; [underlined: Age(s) at outcome assessment:] 11–36 mo (Median: 21 mo, 11–23 mo: 61.0%, 24–36 mo: 39.0%) | [underlined: WLZ (≥1 vs <1) @ 11–36 mo (RR (95% CI))]; Whole grains score: 1.08 (0.80, 1.48); Refined grains score: 1.21 (0.86, 1.71) | [underlined: Key confounders accounted for:] SEP; sex; race and/or ethnicity; milk feeding practices; baseline anthropometry; [underlined: Key confounders NOT accounted for:] gestational age; [underlined: Model adjustments:] WLZ at baseline; [underlined: Funding:] University of Puerto Rico Central Administration Grant; Capacity Advancement in Research Infrastructure; NIMHD
Gaffney, 2014 (https://pubmed.ncbi.nlm.nih.gov/23266435/)^34^; PCS, IFPS II, U.S.; [underlined: Analytic N] = 1,447 (Excluded participants with missing data for the outcome or main exposures of interest); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race/ethnicity:] White: 90.8%, Hispanic: 5.3%, Black: 3.9%; [underlined: Maternal education:] HS or less: 18.7%, Some college: 36.7%, 4-year college or more: 44.6%; [underlined: Other SEP measure(s):] Household income (% of poverty line): <185%: 30.3%, 185 to ≤349%: 30.5%, >349%: 39.1%; [underlined: Maternal age:] 18–24 y: 17.6%, 25–34 y: 64.5%, > 34 y: 17.8%; [underlined: Milk feeding practices:] BF intensity at 2 mo: Low (<20% of milk feedings being BM): 33.1%, Medium/High (≥20% of milk feedings being BM): 66.9%; [underlined: Child sex (female):] 50%; [underlined: Birth size:] NR; [underlined: Gestational age:] NR | [underlined: Exposure(s) and comparator(s):] Cereal (added to baby bottle; Yes vs No (ref)); [underlined: Dietary assessment methods:] Questionnaire completed by mother; [underlined: Age(s) at dietary assessment:] 2 mo; [underlined: Amounts consumed:] Yes: 11.7%, No: 88.3%; [underlined: Outcome(s):] Weight gain; [underlined: Outcome assessment methods:] Weight at last doctor's visit reported by mother; [underlined: Age(s) at outcome assessment:] 6 mo | [underlined: Weight gain (lb) from birth to 6 mo (β)]; Mothers with PPD: 0.15, p=0.03; Among mothers without PPD: 0.02, p=0.80 | [underlined: Key confounders accounted for:] SEP; sex; race and/or ethnicity; milk feeding practices; [underlined: Key confounders NOT accounted for:] gestational age; baseline anthropometry; [underlined: Model adjustments:] Maternal race/ethnicity, age at childbirth, maternal education, household income, pre-pregnancy BMI, postpartum smoking status, infant sex, perceived infant fussiness to be a problem at 2 mo, BF intensity at 2 mo, added cereal to baby bottle at 2 mo, introduction to solid foods; [underlined: Funding:] NR
Garden, 2011 (https://pubmed.ncbi.nlm.nih.gov/21346718/)^30^; PCS, CAPS, Australia; [underlined: Analytic N] = 362 (Excluded participants with missing data on diet or anthropometrics); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race/ethnicity:] Grandparents ethnicity/country of birth: Caucasian: 55%, European: 9%, Middle Eastern: 4%, Indian: 5%, Asian: 4%, Undefined: 24%; [underlined: Maternal education:] NR; [underlined: Other SEP measure(s):] Paternal education: ≤10 y: 33%, 11–12 y: 18%, Tertiary education: 48%; [underlined: Maternal age:] NR; [underlined: Milk feeding practices:] BF ≥6 mo: 42%; [underlined: Child sex (female):] 49%; [underlined: Birth weight:] 3,493 (492) g; [underlined: Gestational age:] NR; [underlined: Other relevant characteristics:] Secondary analysis of RCT (testing intervention of house dust mite avoidance and omega-3 supplementation); all children recruited at increased risk of developing asthma | [underlined: Exposure(s) and comparator(s):]; Continuous (amounts; as tertiles, quartiles, or quintiles); Cereal foods: bread, pasta, rice, breakfast cereals; Cereal-based foods: cookies, crackers, doughnuts, cakes, pies, buns, muffins, pizza; [underlined: Dietary assessment methods:] 3-d weighed food records; [underlined: Age(s) at dietary assessment:] 18 mo; [underlined: Amounts consumed:] Quintiles of grams (g); % total energy intake; Cereal foods: 6, 37, 51, 68, 95; 1, 9, 12, 16, 21; Cereal-based foods: 0, 8, 17, 28, 51; 0, 3, 6, 10, 14; [underlined: Outcome(s):] BMI, waist circumference; [underlined: Outcome assessment methods:] Weight, length, and waist circumference measured by study nurses; [underlined: Age(s) at outcome assessment:] 8 y | [underlined: BMI @ 8 y (β (95% CI))]; Cereal foods, per quintile; g: 0.16 (−0.05, 0.37), p for trend=0.14; % of total energy: 0.12 (−0.08, 0.33), p for trend=0.23; Cereal-based foods, per quintile; g: −0.23 (−0.44, −0.22), p for trend=0.03; % of total energy: −0.27 (−0.47, −0.07), p for trend=0.01; [underlined: WC (cm) @ 8 y (β (95% CI))]; Cereal foods, per quintile; g: 0.35 (−0.21, 0.91), p for trend=0.22; % of total energy: 0.28 (−0.27, 0.83), p for trend=0.32; Cereal-based foods, per quintile; g: −0.61 (−1.17, −0.05), p for trend=0.03; % of total energy: −0.76 (−1.29, −0.23), p for trend=0.01 | [underlined: Key confounders accounted for:] SEP; sex; race and/or ethnicity; milk feeding practices; gestational age; [underlined: Key confounders NOT accounted for:] baseline anthropometry; [underlined: Model adjustments:] sex, asthma study intervention group, birth weight, breastfeeding for at least 6 months, parental obesity status, ethnicity, smoking in pregnancy and father’s education, total energy intake (food intake in grams only); [underlined: Funding:] The National Health and Medical Research Council of Australia; Cooperative Research Centre for Asthma; New South Wales Department of Health; Children’s Hospital Westmead; University of Sydney, Faculty of Medicine; Commonwealth Department of Health and Aging
Garden, 2012 (https://pubmed.ncbi.nlm.nih.gov/23201761/)^29^; PCS, CAPS, Australia; [underlined: Analytic N] = 298 (Excluded participants who were not still participating in the study at 11.5 y or did not have dietary data.); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race/ethnicity:] NR (Australian born mother: 74%, Australian born father: 69%; Child's grandparents ethnicity/country of birth: Caucasian: ~54%, European: ~9%, Middle Eastern/Indian/Asian: ~12%, Undefined: ~25%); [underlined: Maternal education:] 52% tertiary educated; [underlined: Other SEP measure(s):] Full-time employment: Mother: 49%, Father: 87%; [underlined: Maternal age:] 29.0 (5.1) y; [underlined: Milk feeding practices:] BF duration: 0 to <3 mo: 40%, 3 to <6 mo: 16.8%, ≥6 mo: 43.2%; [underlined: Child sex (female):] 49%; [underlined: Birth weight:] 100% ≥2.5 kg; [underlined: Gestational age:] 100% ≥36 wk; [underlined: Other relevant characteristics:] Secondary analysis of RCT (testing intervention of house dust mite avoidance and omega-3 supplementation); all children recruited at increased risk of developing asthma | [underlined: Exposure(s) and comparator(s):] Intake (amount) at 18 mo (all continuous): Cereal foods (bread, pasta, rice, breakfast cereals, etc); Cereal-based products (cookies, crackers, doughnuts, cakes, pies, buns, muffins, pizza, etc),; [underlined: Dietary assessment methods:] Maternal interview/questionnaire (timing of any) and parent/caregiver completed 3-d weighed food record (2 weekdays and 1 weekend day) (types and amounts); [underlined: Age(s) at dietary assessment:] 18 mo (types and amounts); [underlined: Amounts consumed:] See results for intake data; [underlined: Outcome(s):] BMI trajectory; [underlined: Outcome assessment methods:] Weight and height measured by study nurses. Three BMI trajectories defined using latent basis growth mixture model in relationship to CDC percentiles, stratified by sex.; [underlined: Age(s) at outcome assessment:] 1, 3, 6, 9, 12, 18 mo, 2–5 y (every 6 mo), 8 y, 11.5 y | [underlined: BMI trajectory @ birth−11.5 y (median intake at 18 mo by trajectory group)]; Cereals, including bread, pasta, rice, etc.; Boys: normal trajectory: 60.7 g, early and persistent trajectory: 52.1 g, late BMI increase: 63.4 g, p=0.79; Girls: normal trajectory: 54.2 g, early and persistent trajectory: 59.9 g, late BMI increase: 58.3 g, p=0.87; Cereal based extra foods; Boys: normal trajectory: 18.0 g, early and persistent trajectory: 11.0 g, late BMI increase: 26.7 g, p=0.15; Girls: normal trajectory: 22.5 g, early and persistent trajectory: 28.5 g, late BMI increase: 18.5 g, p=0.56; Results analyzed by % of total energy were similar. | [underlined: Key confounders accounted for:] SEP; sex; race and/or ethnicity; milk feeding practices; baseline anthropometry (multinomial regression only).; [underlined: Key confounders NOT accounted for:] gestational age; [underlined: Model adjustments:] dietary intervention group, BF, parental obesity, ethnicity, smoking during pregnancy, father's education status (multinomial regression only); [underlined: Funding:] National Health and Medical Research Council of Australia
Lande, 2005 (https://pubmed.ncbi.nlm.nih.gov/16106264/)^36^; PCS, Norway; [underlined: Analytic N] = 1,441 (Excluded participants who did not complete semiquantitative FFQs at both 6 mo and 12 mo, were not born full term, and had a ponderal index at birth <10th percentile.); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race/ethnicity:] NR; [underlined: Maternal education:] ≤10 y: 10%, 11–12 y: 41%, ≥13 y: 50%; [underlined: Other SEP measure(s):] NR; [underlined: Maternal age:] <25 y: 12%, 25–34 y: 71%, ≥35 y: 17%; [underlined: Milk feeding practices:] EBF ≥4 mo: ~46%, BF duration: <6 mo: ~16%, 6–11 mo: ~47%, ≥12 mo: ~37%; [underlined: Child sex (female):] 47%; [underlined: Birth length:] 50.8 (2.0) cm; [underlined: Gestational age:] 100% born after 37 completed wk gestation | [underlined: Exposure(s) and comparator(s):] Commercial infant porridge at 6 mo (continuous); [underlined: Dietary assessment methods:] Semiquantitative FFQ completed by mothers/parents; [underlined: Age(s) at dietary assessment:] 6 mo and 12 mo (timing of any only); [underlined: Amounts consumed:] ~169 g/d; [underlined: Outcome(s):] BMI; [underlined: Outcome assessment methods:] Weight and height measured by health-care personnel at child health clinics.; [underlined: Age(s) at outcome assessment:] 6 mo, 12 mo | [underlined: BMI @ 12 mo]; Data NR, p=NS | [underlined: Key confounders accounted for:] SEP; milk feeding practices; gestational age; [underlined: Key confounders NOT accounted for:] sex; race and/or ethnicity; baseline anthropometry; [underlined: Model adjustments:] NA (exposures of interest not retained in model); [underlined: Funding:] Research Council of Norway
Lindholm, 2020 (https://pubmed.ncbi.nlm.nih.gov/33148198/)^37^; PCS, H2GS, Sweden; [underlined: Analytic N] = 1,780 (Excluded participants with missing outcome data, with outcome data measured outside age limits, or born preterm); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race/ethnicity:] NR; [underlined: Maternal education:] Upper secondary school: 39%, Elementary school: 5%, University: 51%, Other: 4%; [underlined: Other SEP measure(s):] NR; [underlined: Maternal age:] <25 y: 14%, 25–35 y: 69%, ≥35: 17%; [underlined: Milk feeding practices:] Predominantly BF: 87% at birth, 67% at 3–4 mo, 29% at 6 mo, 4.5% at 12 mo; Exclusively FF: 6% at birth, 20% at 3–4 mo; [underlined: Child sex (female):] 49%; [underlined: Birth weight:] ~3,600 g; AGA: 92%; [underlined: Gestational age:] 100% full-term | [underlined: Exposure(s) and comparator(s):] Milk cereal drink (“gruel”, liquid complement to BM that is commercially available and made from grains and dehydrated skimmed milk mixed with hot water; yes vs no (ref)); [underlined: Dietary assessment methods:] Parent questionnaires; [underlined: Age(s) at dietary assessment:] 6 mo; [underlined: Amounts consumed:] Milk cereal drink at 6 mo: 44%; [underlined: Outcome(s):] RWG; [underlined: Outcome assessment methods:] Weight measured by study personnel. Weight transformed to sex- and age-specific SDS using Swedish reference data. RWG defined as change >0.67 weight SDS.; [underlined: Age(s) at outcome assessment:] 6 mo, 12 mo | [underlined: RWG from 6–12 mo (OR (95% CI))] 1.00 (0.64, 1.57), p=0.985 | [underlined: Key confounders accounted for:] SEP; sex; milk feeding practices; gestational age; [underlined: Key confounders NOT accounted for:] race and/or ethnicity; baseline anthropometry; [underlined: Model adjustments:] Birth weight, sex, maternal and paternal education, maternal and paternal smoking, maternal weight before pregnancy, maternal gestational weight gain, paternal weight at the first measurement point, maternal and paternal diabetes and cardiovascular disease, BF, bottle-feeding, nighttime meals; [underlined: Funding:] SEP; sex; milk feeding practices; gestational age
Lundkvist, 2021 (https://pubmed.ncbi.nlm.nih.gov/34208982/)^38^; PCS, NorthPop, Sweden; [underlined: Analytic N] = 1,499 (Excluded participants without anthropometric data at 18 (±1) mo and those born <37 wk.); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race/ethnicity:] NR; [underlined: Maternal education:] Primary: 0.7%, Lower secondary: 2.7%, Upper secondary: 24%, Post secondary: 69%, Post-graduate (including doctoral degree): 3.1%; [underlined: Other SEP measure(s):] Household disposable income: 526,058 SEK; Co-parent education: Primary: 0.4%, Lower secondary: 3.0%, Upper secondary: 38%, Post-secondary: 46%, Post-graduate (including doctoral degree): 2.7%; [underlined: Maternal age:] 30.9 (4.5) y; [underlined: Milk feeding practices:] NR; [underlined: Child sex (female):] 49%; [underlined: Birth weight:] 3,594 (478) g; LBW: 0.7%, Normal weight: 95.9%, Macrosomia: 3.5%; [underlined: Gestational age:] 40 (1.3) wk; 100% term | [underlined: Exposure(s) and comparator(s):] Milk cereal drink: frequent consumers (daily), consumers (monthly and weekly), nonconsumers; [underlined: Dietary assessment methods:] FFQ (1 mo recall); [underlined: Age(s) at dietary assessment:] 9 mo; [underlined: Amounts consumed:] Frequent consumers: 52.3%, Consumers: 16.8%,s Nonconsumers: 30.9%; [underlined: Outcome(s):] BMIZ, overweight; [underlined: Outcome assessment methods:] Weight and length derived from child health care records. Sex- and age-specific BMIZ calculated using WHO standards.; Overweight defined as BMIZ > 2.; [underlined: Age(s) at outcome assessment:] 18 mo | [underlined: BMIZ @ 18 mo]; Frequent consumers vs Consumers vs Nonconsumers: Data NR, NS; [underlined: Overweight @ 18 mo]; Frequent consumers vs Consumers vs Nonconsumers: Data NR, NS | [underlined: Key confounders accounted for:] sex; milk feeding practices; gestational age; [underlined: Key confounders NOT accounted for:] SEP; race and/or ethnicity; baseline anthropometry; [underlined: Model adjustments:] BMIZ: fruit juice at 18 mo, breastfeeding at 9 mo, maternal BMI; Overweight: None; [underlined: Funding:] Swedish Research Council; Region Vasterbotten; Umea University
Moore, 2019 (https://pubmed.ncbi.nlm.nih.gov/31766167/)^40^; PCS, Nurture, U.S.; [underlined: Analytic N] = 466 (Reasons for attrition NR); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race/ethnicity:] Black: 71.5%, White: 19.2%, Other: 8.9%; Latina: 6.5%; (Child race and/or ethnicity: Black: 68.6%, White: 15.0%, White: 14.9%, Latina: 8.9%); [underlined: Maternal education:] ≤ HS diploma: 47.8%; Some college: 30.3%; College graduate: 15.5%; Graduate degree: 6.3%; [underlined: Other SEP measure(s):] Household income: ≤$20k: 55.4%, $20–40k: 19.1%, >$40k: 16.7%; [underlined: Maternal age:] 27.1 (5.8) y; [underlined: Milk feeding practices:] BF duration: 14.7 (18.2) wk; [underlined: Child sex (female):] 49%; [underlined: Birth weight-for-gestational age z-score:] −0.31 (0.9); [underlined: Gestational age:] 100% ≥37 wk | [underlined: Exposure(s) and comparator(s):] Baby snacks (teething biscuits, puffs, melts): never, sometimes, often; [underlined: Dietary assessment methods:] Infant feeding questionnaire from IFPS II and FITS completed by mother: home visit (3, 6, 9, 12 mo); interactive voice response telephone calls (1, 2, 4, 5, 7, 8, 10, 11 mo); [underlined: Age(s) at dietary assessment:] 1–12 mo (monthly); [underlined: Amounts consumed:] Baby snacks, frequency median (IQR): 0–3 mo: 0.0 x/d (0.0, 0.0), 4–6 mo: 0.0 x/d (0.0, 1.0), 7–9 mo: 2.7 x/d (1.3, 3.7), 10–12 mo: 3.0 x/d (2.0, 4.0); Sweets, frequency median (IQR): 0–3 mo: 0.0 x/d (0.0, 0.0), 4–6 mo: 0.0 x/d (0.0, 0.0), 7–9 mo: 0.0 x/d (0.0, 1.0), 10–12 mo: 0.7 x/d (0.0, 1.7); [underlined: Outcome(s):] WLZ; [underlined: Outcome assessment methods:] Weight and length were measured by study personnel. Age- and sex-specific WLZ calculated using WHO reference standards.; [underlined: Age(s) at outcome assessment:] 3 mo, 6 mo, 9 mo, 12 mo | [underlined: WLZ @ 6 mo (β (SE))]; Baby snacks at 4–6 mo; Sometimes vs Never (ref): 0.11 (0.07), p=NS Often vs Never (ref): −0.08 (0.10), p=NS; [underlined: WLZ @ 9 mo (β (SE))]; Baby snacks at 7–9 mo; Sometimes vs Never (ref): −0.12 (0.11), p=NS Often vs Never (ref): 0.07 (0.12), p=NS; [underlined: WLZ @ 12 mo (β (SE))]; Baby snacks at 10–12 mo; Sometimes vs Never (ref): −0.14 (0.11), p=NS Often vs Never (ref): 0.02 (0.13), p=NS | [underlined: Key confounders accounted for:] SEP; sex; race and/or ethnicity; milk feeding practices; gestational age; [underlined: Key confounders NOT accounted for:] baseline anthropometry; [underlined: Model adjustments:] birth weight-for-gestational age z-scores, total weeks of any breastfeeding; [underlined: Funding:] NIH
Ventura, 2019 (https://pubmed.ncbi.nlm.nih.gov/30569642/)^42^; PCS, IFPS II, U.S.; [underlined: Analytic N] = 695 (Excluded participants with implausible WAZ scores (> 5 or <-5), with missing data on birth weight and fewer than 2 weight measurements, where the mother was away from infant more than 70 h/wk at any assessment, where mother reported infant had a serious health problem at any age, with missing data on any predictor or outcome variables, and infants who did not have high risk bottle-feeding (high-stable use and rapid increase).); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race/ethnicity:] Minority race/ethnicity (minority not defined in paper): 13%; [underlined: Maternal education:] HS degree or less: 23%; [underlined: Other SEP measure(s):] WIC participation: 38%; Poverty-to-income ratio level, percent of poverty level: ~292%; [underlined: Maternal age:] ~30 y; [underlined: Milk feeding practices:] BM-feeding intensity (% of daily milk feedings that were BM), 0–6 mo: ~11%; [underlined: Child sex (female):] 50%; [underlined: Birth weight:] ~8 lb; [underlined: Gestational age:] ~39 wk; [underlined: Other relevant characteristics:] Analysis limited to infants with “high risk bottle use” (high-stable bottle use and rapid increase in bottle use) | [underlined: Exposure(s) and comparator(s):] Cereal (added to bottle of formula or BM; continuous); [underlined: Dietary assessment methods:] FFQ of infant’s diet in past 7 days completed by mothers; [underlined: Age(s) at dietary assessment:] 1, 2, 3, 4, 5, 6 mo; [underlined: Amounts consumed:] NR; [underlined: Outcome(s):] RWG; [underlined: Outcome assessment methods:] Maternal report of infant’s measured weight and length at last pediatrician visit. Weight standardized to age- and sex-specific WAZs based on WHO child growth standards. RWG defined as difference between WAZ from birth to last weight assessed between 6 and 12 mo ≥0.67.; [underlined: Age(s) at outcome assessment:] 3, 5, 7, 12 mo | [underlined: No RWG from birth to 6–12 mo (OR (95% CI))]; 0.82 (0.69, 0.97), p<0.05 | [underlined: Key confounders accounted for:] SEP; sex; race and/or ethnicity; milk feeding practices; gestational age; [underlined: Key confounders NOT accounted for:] baseline anthropometry; [underlined: Model adjustments:] Child sex, gestational age, birth weight, maternal age, pre-pregnancy obesity, smoking during pregnancy, parity, poverty-income ratio level, WIC participation, education level, race/ethnicity, BM-feeding intensity, frequency of bottle-to-bed, frequency of cereal in bottle, frequency of infant-led bottle-emptying, frequency of maternal encouragement of bottle-emptying, frequency of feedings, early introduction to CFB; [underlined: Funding:] NR

a Abbreviations: @: at; AGA: appropriate for gestational age; β: beta; BF: breastfeeding; BM: breastmilk; BMI: body mass index; BMIZ: BMI z-score; CAPS: Childhood Asthma Prevention Study; CDC: Centers for Disease Control and Prevention; CI: confidence interval; cm: centimeter; d: day; EBF: exclusive breastfeeding; etc: et cetera; Fe: iron; FF: formula feeding; FFQ: food-frequency questionnaire; FITS: Feeding Infants and Toddlers Study; g: gram; h: hour; H2GS: Halland Health and Growth Study; HC: head circumference; HCZ: head circumference z-score; HS: high school; IFPS II: Infant Feeding Practices Study II; IQR: interquartile range; kg: kilogram; LAZ: length-for-age z-score; LBW: low birthweight; lb: pound; mo: month; NA: not applicable; NCHS: National Center for Health Statistics; NR: not reported; NS: non-significant; OR: odds ratio; PCS: prospective cohort study; RCT: randomized controlled trial; RR: risk ratio; RWG: rapid weight gain; SD: standard deviation; SDS: standard deviation score; SE: standard error; SEK: Swedish Krona; SEP: socioeconomic position; SGA: small for gestational age; svg: serving; U.S.: United States; vs: versus; WAZ: weight-for-age z-score; WC: waist circumference; WHO: World Health Organization; WIC: Special Supplemental Nutrition Program for Women, Infants, and Children; wk: week; WLZ: weight-for-length z-score; x: times; y: year; Zn: zinc

Table 40 Risk of bias for randomized controlled trials (parallel) examining grains consumption and growth, body composition, and risk of obesity ^a^

Article | Randomization | Deviations from intended interventions (effect of assignment or per-protocol) | Missing outcome data | Outcome measurement | Selection of the reported result | Overall risk of bias
Krebs, 2006^35^ | SOME CONCERNS | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS

a Possible ratings of low, some concerns, or high determined using the "Cochrane Risk-of-bias 2.0" (https://www.riskofbias.info/welcome/rob-2-0-tool) (RoB 2.0) (August 2019 version)” ( Sterne JAC, Savović J, Page MJ, Elbers RG, Blencowe NS, Boutron I, Cates CJ, Cheng H-Y, Corbett MS, Eldridge SM, Hernán MA, Hopewell S, Hróbjartsson A, Junqueira DR, Jüni P, Kirkham JJ, Lasserson T, Li T, McAleenan A, Reeves BC, Shepperd S, Shrier I, Stewart LA, Tilling K, White IR, Whiting PF, Higgins JPT. RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ 2019; 366: l4898.31462531

Table 41 Risk of bias for randomized controlled trials (cluster) examining grains consumption and growth, body composition, and risk of obesity ^b^

Article | Randomization | Timing of identification and recruitment of individual participants in relation to timing of randomization | Deviations from the intended interventions (effect of assignment/adhering to intervention) | Missing outcome data | Outcome measurement | Selection of the reported result | Overall risk of bias
Ma, 2016^39^ | HIGH | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | HIGH
Tang, 2014^41^ | HIGH | SOME CONCERNS | LOW | LOW | LOW | LOW | HIGH

b Possible ratings of low, some concerns, or high determined using the "Cochrane Risk-of-bias 2.0" (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2019 version)” ( Sterne JAC, Savović J, Page MJ, Elbers RG, Blencowe NS, Boutron I, Cates CJ, Cheng H-Y, Corbett MS, Eldridge SM, Hernán MA, Hopewell S, Hróbjartsson A, Junqueira DR, Jüni P, Kirkham JJ, Lasserson T, Li T, McAleenan A, Reeves BC, Shepperd S, Shrier I, Stewart LA, Tilling K, White IR, Whiting PF, Higgins JPT. RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ 2019; 366: l4898.31462531

Table 42 Risk of bias for observational studies examining grains consumption and growth, body composition, and risk of obesity ^a^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Almquist-Tangen, 2013^32^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Almquist-Tangen, 2019^33^ (milk cereal drink at 12 mo) | SOME CONCERNS | SOME CONCERNS | LOW | LOW | HIGH | LOW | HIGH | HIGH
Almquist-Tangen, 2019^33^ (all other exposures) | VERY HIGH | SOME CONCERNS | LOW | LOW | HIGH | LOW | HIGH | VERY HIGH
Amaro-Rivera, 2019^1^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Gaffney, 2014^34^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | HIGH | SOME CONCERNS | SOME CONCERNS | HIGH
Garden, 2011^30^ | SOME CONCERNS | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Garden, 2012^29^ | SOME CONCERNS | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Lande, 2005^36^ | HIGH | LOW | LOW | LOW | HIGH | LOW | HIGH | HIGH
Lindholm, 2020^37^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Lundkvist, 2021^38^ (overweight) | VERY HIGH | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | VERY HIGH
Lundkvist, 2021^38^ (BMIZ) | HIGH | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Moore, 2019^40^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Ventura, 2019^42^ | SOME CONCERNS | LOW | LOW | LOW | HIGH | SOME CONCERNS | SOME CONCERNS | HIGH

a Possible ratings of low, some concerns, high, very high, no information, or not applicable determined using the "Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)" tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602. ) *Low risk of bias except for concerns about uncontrolled confounding.

### Protein foods

#### Description of the evidence

Ten studies (13 articles) met inclusion criteria and examined the relationship between the consumption of foods from the protein foods group by infants and young children, up to age 24 months, and growth, body composition, and risk of obesity (Table 44).^1,27,29–3^,^1,35,39,4^,^1,43–47^ Two studies (3 articles) were parallel RCTs^35,46,47^ and 1 study (2 articles) was a cluster-RCT.^39,41^ Seven studies (8 articles) were PCS,^1,27,29–31,43–45^ using data from the following cohorts: the All Children in South-East Sweden,^43^ CAPS,^29,30^ LoTiS,^31^ Born in Bradford 1000,^27^ the Feeding Queensland Babies Study Cohort,^45^ and 2 unnamed studies^1,44^ One PCS was a secondary analysis of a RCT testing the impact of dust mite avoidance and omega-3 fatty acid supplementation on asthma prevention.^29,30^

##### Population

The studies were conducted in several countries including Australia,^29,30,45^ China,^31,39,41^ Sweden,^43^ the United Kingdom,^27,44^ and the United States,^1,35,46,47^ including 1 study from Puerto Rico.^1^ The analytic sample sizes of the RCTs ranged from 53^46^ to 1,318.^41^ For the PCS, the analytic sample sizes ranged from 25^45^ to 6,749.^43^ Regarding power, 1 article reported that the study was powered for outcomes related to growth,^47^ 1 article reported that the study did not meet the sample size goal based on a power calculation for outcomes related to growth, body composition, or risk of obesity,^35^ while the remaining studies did not provide any information on power.

Race and/or ethnicity varied across the 7 studies that reported this information. Specifically, 75% or more of the participants were White in 2 studies,^44,46,47^ approximately 90% of children had 2 Swedish parents in 1 study,^43^ 100% of participants were Hispanic in ^1^ study,1 100% of participants were Chinese in 1 study,^39,41^ approximately 55% and 45% of participants were Pakistani and White British, respectively, in 1 study,^27^ and the ethnicity/country of birth of the children’s grandparents in 1 study were varied including Caucasian (55%), European (9%), Middle Eastern (4%), Indian (5%), Asian (4%), and undefined (24%).^29,30^ Of the 6 studies that reported maternal age, most reported that the average age was approximately 30 years,^29,31,43,46,47^ with 1 study reporting that 64% were age 31 to 40 years^44^ and 1 study reporting that approximately 56% were younger than age 30 years.^1^ Among the RCTs, 2 studies enrolled infants age 4–6 months who were exclusively breast feeding,^35,39,41^ while 1 study enrolled infants age 5 months who were exclusively formula feeding.^46,47^ Of the 5 PCS that reported information on human milk feeding,^1,29–31,43,44^ a range of practices were reported. Specifically 2 studies reported an average duration of breast feeding of approximately 7 to 8 months,^31,43^ 2% of infants breast fed at age 6 months in 1 study,^44^, approximately 43% of infants were breast fed for 6 months or longer in 1 study,^29,30^ and approximately 21% of infants were breast fed at age 10 months.^1^ Five studies provided information on measures of SEP.^1,29,30,4^,^1,43,44^ The most common SEP measure was maternal education, with reported education levels including approximately 55% with at least 9 years of education in 1 study,^41^ approximately 68% with greater than a high school education in a second study,^1^ approximately 35% with a college or university education in a third study,^43^ and approximately 52% with tertiary education in the last study.^29^ Employment was reported across 3 studies and varied widely, with 1 study reporting that only 7% of women were participating in paid work,^41^ a second study reporting that 49% were employed full-time,^29^ and the third noting that over 75% of participants had either “higher” or “intermediate” occupations.^44^ One study noted that household disposable income was either “high” or “medium” in over 80% of participants,^43^ while another study exclusively enrolled individuals participating in WIC.^1^

The children enrolled in these studies were approximately 50% female.^1,29–3^,^1,35,39,43–47^ Among studies reporting birth size, the average birth weight predominantly ranged from approximately 3.2 kilograms to 3.6 kilograms,^2,27,29,30,35,39,43,44,46,47^ although 1 study of twins reported an average birth weight of 2.5 kilograms.^31^ Additionally, 3 studies reported that 100% of participants had a birth weight greater than or equal to 2.0 kilograms^39^ or 2.5 kilograms.^29,44^ With the exception of the study of twins, which reported that 53% of the children were born preterm,^31^ the studies predominantly focused on infants born term with 4 reporting that 100% of the included children were born term or at 36 weeks gestation and later^29,35,39,41,44^ and 2 studies reporting that the average gestational age at birth was 39 to 40 weeks.^43,46,47^ Across the RCTs, 1 reported small, but statistically significant, differences in infant length between the intervention and comparator groups at baseline, but analyses were adjusted for baseline length and LAZ,^41^ while the other 2 RCTs reported that baseline anthropometry did not vary by intervention group.^35,47^ The PCS did not report baseline anthropometry by level of exposure^30,31^ or did not report baseline anthropometry.^1,27,29,43,45,46^

##### Interventions/exposures and comparators

The studies examined a variety of foods from the protein foods group, although nearly all focused on animal sources. Among the RCT, all 3 compared consumption of meat (beef,^35^ pork,^39,41^ or beef and ham^46,47^) to consumption of infant cereal (fortified^35,39,41^ or unfortified^39,41^) or dairy-based complementary foods.^46,47^ While 1 study aimed to compare different food sources of the macronutrient protein,^46,47^ the 2 studies that compared meat to infant cereal noted interest in the contribution of meat to intake of protein, iron, and zinc.^35,39,41^ The interventions began at age 4 to 6 months and ranged in duration from approximately 2^35^ to 12^39,41^ months. Compliance to the assigned group was high in the 1 RCT that reported this information.^46,47^ Among the PCS, a broader range of exposures were examined including: red meat and poultry^29,30,44^; red meat, poultry, and seafood^31^; red meat, poultry, seafood, and eggs^45^; seafood^43^; processed meat products (undefined)^27^; and meat (undefined) and beans.^1^ Five studies used FFQs to assess consumption of protein foods,^1,27,3^,^1,43,45^ while the remaining 2 studies used a weighed food record or diary.^29,30,44^ All of the PCS assessed protein foods consumption at or after age 12 months, but 2 studies additionally examined protein foods consumption prior to age 12 months.^1,44^

##### Outcomes

Growth, body composition, and risk of obesity were assessed using a variety of measures. Outcomes related to growth were the most frequently reported^27,29–31,35,39,41,44–47^ and most commonly included weight, WAZ, length, LAZ, BMIZ, head circumference, and head circumference z-score. Body composition,^30,31,45^ and risk of overweight and/or obesity^1,43^ were less frequently assessed. Measures of body composition included waist circumference,^30^ body fat mass and percentage,^3^,^1^ and fat mass index, fat-free mass index, and waist-to-height ratio z-scores.^45^ Among studies that utilized z-scores, most reported using CDC^29,35,46,47^ or WHO^1,27,31,39,41,45–47^ growth standards to calculate z-scores. The outcomes were measured by study personnel in all studies except for 1, in which weight and height were reported by the parents and then subsequently validated between health clinic charts.^43^ The age at which the outcomes were measured varied greatly, ranging from age 4 months^35,44^ to age 11.5 years,^29^ although most outcomes were measured up to age 24 months.^1,31,35,39,4^,^1,44,46,47^

#### Synthesis of the evidence

Of the 10 studies that analyzed the relationship between protein foods consumption and growth, body composition, and risk of obesity, 5 studies reported a mix of statistically significant and non-significant findings,^29,30,35,39,41,45–47^ while 5 studies reported exclusively null results^1,27,3^,^1,43,44^ (Table 44). Two of these 10 studies only reported correlations.^31,45^

All 3 RCTs reported mixed results.^35,39,41,46,47^ Two of the RCTs found that infants consuming meat-based complementary foods tended to have greater or greater increases in length or LAZ compared to infants consuming infant cereal^39,41^ or dairy based complementary foods,^46,47^ while differences between intervention groups for other outcomes such as weight, WAZ, WLZ, and head circumference were not detected. The generalizability of 1 of these RCTs to the United States is limited, due to the study location’s moderately high stunting rate.^39,41^ Finally, while monthly change in head circumference from age 7 to 12 months, but not from age 4 to 7 months, was greater among infants consuming meat, compared to iron-fortified infant cereal, at the beginning of complementary feeding, group differences were not detected for monthly change in weight, length, and weight-for-length percentile.^35^ Two PCS also detected that protein foods consumption was significantly associated with several outcomes.^29,30,45^ Specifically, greater consumption of meat and poultry combined at age 18 months was associated with higher BMI and waist circumference at age 8 years, and less favorable BMI trajectories (among boys) from birth to age 11.5 years in 1 study,^29,30^ while more frequent consumption of meat, fish, and eggs combined at age 12 months was correlated with greater fat-free mass index and waist-to-height ratio z-scores, but not BMIZ or fat mass index z-score, at age 2–3 years in the other.^45^

The remaining 5 studies, all from PCS, did not detect associations between protein foods consumption and growth, body composition, or risk of obesity.^1,27,3^,^1,43,44^ These studies tended to report non-significant differences of small magnitude in outcomes by protein foods consumption^1,27,31^ or simply reported statistical significance.^43,44^ There was considerable variability in the exposures, outcomes, and the ages in which these variables were assessed across these studies. Exposures examined in these studies were assessed at ages 4 months up to 24 months and included amounts of red and white meat,^44^ frequency of meats (including poultry and seafood),^31^ amounts of meat (undefined) and beans,^1^ frequency of fatty-fish,^43^ and frequency of processed meat products (undefined).^27^ The outcomes were assessed at time points between age 12 months and 8 years,^43^ and included a wide range of measures including BMIZ,^27,31^ WAZ,^31^ weight,^31,44^ HAZ,^31^ length,^31,44^ head circumference,^44^ body fat mass and percentage,^31^ weight status,^43^ and WLZ ≥1.^1^

There were several important limitations across the body of evidence. First, few studies examined protein foods as a food group comprehensively and directly. Instead, most studies focused on smaller subsets of foods from the protein foods group, most commonly meats alone or in combination with poultry and/or seafood. Only 1 study reported including both animal and plant sources of protein foods and few studies reported including seafood or eggs. Second, there was considerable heterogeneity across the studies on a variety of factors. The studies examined a wide range of interventions and exposures, some assessing single foods or small groups of foods (e.g., beef, pork, fatty fish, processed meat) while other examined broader combinations of protein foods. Few studies analyzed the same combinations of foods from the protein foods group in their assessment, adding to the heterogeneity of the exposures. Additionally, the comparators varied, with trials comparing consumption of meat to consumption of infant cereal and dairy, and the PCS comparing differing amounts in some and differing frequency in others.

#### Conclusion statement and grade

The Committee did not draw a conclusion statement about the relationship between consumption of protein foods as a food group by infants and young children, up to 24 months, and growth, body composition, and risk of obesity (Table 43). This was due to substantial concerns with consistency and directness in the body of evidence. Across the studies, there was marked heterogeneity in the interventions, exposures, and comparators examined. Additionally, few studies examined protein foods as a food group collectively. Instead, most studies examined subsets of this food group, such as meats alone; few studies examined eggs or beans. Publication bias was also a consideration; however, this was not assessed as a serious concern because the body of evidence included studies that reported only nonsignificant findings as well as studies that reported a mix of both significant and nonsignificant results, across a range of analytic sample sizes. However, while the literature search was comprehensive, a search of the gray literature was not done, which could increase the possibility of publication bias. The risk of bias assessments for the studies that addressed this question are documented in Table 45, Table 46, and Table 47, for parallel-RCT, cluster-RCT, and PCS, respectively.

Table 43 Conclusion statement, grade for consumption of protein foods by infants and young children and growth, body composition, and risk of obesity

Conclusion Statement | A conclusion statement cannot be drawn about the relationship between consumption of protein foods as a food group by infants and young children, up to age 24 months, and outcomes related to growth patterns, body composition, and risk of obesity during childhood because of substantial concerns with consistency and directness in the body of evidence.
Grade | Grade Not Assignable
Body of Evidence | 13 articles (10 studies): 3 parallel randomized controlled trials (5 articles), 7 prospective cohort studies (8 articles)
Rationale | The studies varied substantially in the types of protein foods examined and the comparators. Few studies directly examined protein foods as a food group.

Table 44 Evidence examining the relationship between consumption of protein foods and growth, body composition, and risk of obesity ^a^

Study and Participant Characteristics | Intervention/Exposure, Comparator, and Outcome | Results | Key Confounders, Model Adjustments, Funding
Parallel-RCT
Krebs, 2006 (https://pubmed.ncbi.nlm.nih.gov/16456417/)^35^; RCT-Parallel, U.S.; [underlined: Analytic N by group:] Meat: n=38, Cereal: n=34; [underlined: Attrition:] Meat: 18%, Cereal: 18% (Excluded participants who dropped out due to inability to continue EBF, return to work, relocation); [underlined: Adequately powered:] No; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race/ethnicity:] NR; [underlined: Maternal education:] NR; [underlined: Other SEP measure(s):] NR; [underlined: Maternal age:] NR; [underlined: Milk feeding practices:] 100% EBF at 4 mo; [underlined: Child sex (female):] 51%; [underlined: Birth weight:] ~3.37 kg; [underlined: Gestational age:] 100% born at term | [underlined: Intervention(s):] Meat group: Received pureed beef (Gerber Beef and Beef Gravy, Second Foods) as first complementary food from ~4–6 mo - 7mo; deferred introduction of infant cereal until after 7 mo; encouraged to wait until ~5 months to start complementary food; [underlined: Comparator(s):] Cereal group: Received Fe-fortified cereal from ~4–6 mo - 7mo (Gerber Fe fortified infant rice cereal, without Zn, First Foods) as first complementary food, mixed with either expressed human milk or water on approximately a 1:2 ratio of cereal to fluid; deferred introduction of meats/other high protein foods until after 7 mo; encouraged to wait until ~5 months to start complementary food; [underlined: Dietary assessment methods:] 3-d diet records; [underlined: Compliance:] NR; [underlined: Age at intervention:] ~4–6 mo - 7 mo; [underlined: Intervention duration:] ~2 mo; [underlined: Outcome(s):] Weight, length, HC, weight- for-length; [underlined: Outcome assessment methods:] Weight, length, and head circumference were measured by trained study nurses.; Percentiles for weight-for-length for age based on CDC data.; [underlined: Age(s) at outcome assessment:] 4 mo, 5 mo, 6 mo, 7 mo, 9 mo, 12 mo | [underlined: Monthly weight change (g) from 4–7 mo and 7–12 mo (mean (SE))]; Meat vs Cereal; From 4–7 mo: 399 (20) vs 427 (21), p=NS; From 7–12 mo: 267 (17) vs 252 (18), p=NS; [underlined: Monthly length change (cm) from 4–7 mo and 7–12 mo (mean (SE))]; Meat vs Cereal; From 4–7 mo: 1.62 (0.062) vs 1.78 (0.065), p=NS; From 7–12 mo: 1.25 (0.046) vs 1.27 (0.048), p=NS; [underlined: Monthly HC change (cm) from 4–7 mo and 7–12 mo (mean (SE))]; Meat vs Cereal; From 4–7 mo: 0.79 (0.028) vs 0.81 (0.028), p=NS; From 7–12 mo: 0.48 (0.018) vs 0.41 (0.019), p=0.02; [underlined: Monthly weight-for-length percentile from 4–7 mo and 7–12 mo (mean)]; Meat vs Cereal; At 4–7 mo: Data NR, p=NS At 7–12 mo: Data NR, p=NS | [underlined: Model adjustments:] Birth weight, gestational age, sex; [underlined: Funding:] National Cattleman's Beef Association, NIH, Gerber Products Company (food provision)
Tang, 2018 (https://pubmed.ncbi.nlm.nih.gov/29722841/)^47^; RCT-Parallel, U.S.; [underlined: Analytic N by group:] Meat: n=32, Dairy: n=32; [underlined: Attrition:] Meat: 8.6%, Dairy: 11.1% (Excluded participants who moved, were not compliant, switched formula, or lost contact); [underlined: Adequately powered:] Yes; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race/ethnicity:] White: ~75%, Hispanic: ~17.5%, Black: ~4.5%, Asian: ~3%; [underlined: Maternal education:] NR; [underlined: Other SEP measure(s):] NR; [underlined: Maternal age:] ~30 y; [underlined: Milk feeding practices:] 100% exclusively formula-fed infants; [underlined: Child sex (female):] ~53.5%; [underlined: Birth weight:] ~3.3 kg; [underlined: Gestational age:] ~39 wk | [underlined: Intervention(s):] Meat-based complementary foods (pureed meats) from 5 mo to 12 mo of age in addition to infant formula (same formula given to both groups). (Total protein intake, including formula, ~3g/kg/d.) Fruit and vegetable intake not restricted.; [underlined: Comparator(s):] Dairy-based complementary foods (infant yogurt, cheese, powdered concentrate of 80% whey protein) from 5 mo to 12 mo of age in addition to infant formula (same formula given to both groups). (Total protein intake, including formula, ~3g/kg/d.) Fruit and vegetable intake not restricted.; [underlined: Dietary assessment methods:] Parental report via calendars to record daily consumption, 3-d diet records completed monthly. Return of unused foods, if any.; [underlined: Compliance:] Intervention: Protein from meat-based CF at 10 mo −2.1 g/kg/d, Protein from dairy-based CF at 10 mo −0.03 g/kg/d; Comparator: Protein from meat-based CF at 10 mo −0.01 g/kg/d, Protein from dairy-based CF at 10 mo −2.0 g/kg/d; [underlined: Age at intervention:] 5–12 mo; [underlined: Intervention duration:] 7 mo; [underlined: Outcome(s):] Weight, WAZ, Length, LAZ, WLZ, Head circumference, Head circumference Z-score; [underlined: Outcome assessment methods:] Length, weight, and head circumference measured by blinded, trained research personnel. Z-scores calculated using WHO/CDC growth standards.; [underlined: Age(s) at outcome assessment:] 5, 7, 8, 9, 10, 11, and 12 mo | [underlined: Weight (kg) @ 5 mo - 12 mo (Mean (SD))]; Meat vs Dairy; Group x time interaction: p=0.81; 5 mo: 7.37 (0.67) vs 7.35 (0.74), p=NS; 7 mo: 8.17 (0.70) vs 8.10 (0.77), p=NR; 8 mo: 8.63 (0.78) vs 8.49 (0.74), p=NR; 9 mo: 8.90 (0.75) vs 8.91 (0.75), p=NR; 10 mo: 9.28 (0.78) vs 9.23 (0.78), p=NR; 11 mo: 9.61 (0.81) vs 9.51 (0.79), p=NR; 12 mo: 9.92 (0.91) vs 9.92 (0.97), p=NR; [underlined: Length (cm) @ 5 mo - 12 mo (Mean (SD))]; Meat vs Dairy; Group x time interaction: p=0.0002; 5 mo: 65.3 (2.2) vs 65.3 (2.5), p=NS; 7 mo: 68.1 (2.7) vs 67.3 (2.2), p=NR; 8 mo: 69.5 (2.4) vs 68.5 (2.3), p=NR; 9 mo: 71.0 (2.3) vs 69.9 (2.5), p=NR; 10 mo: 72.5 (2.6) vs 71.2 (2.4), p=NR; 11 mo: 73.8 (2.6) vs 72.3 (2.3), p=NR; 12 mo: 75.7 (2.6) vs 73.9 (2.2), p=NR; [underlined: HC (cm) @ 5 mo - 12 mo (Mean (SD))]; Meat vs Dairy; Group x time interaction: p=0.55; 5 mo: 43.0 (1.2) vs 43.1 (1.1), p=NS; 12 mo: 46.4 (1.3) vs 46.3 (1.1), p=NR; [underlined: HCZ @ 5 mo - 12 mo (Mean (SD))]; Meat vs Dairy; Group x time interaction: p=0.41; 5 mo: 0.51 (0.82) vs 0.54 (0.77), p=NS; 7 mo: 0.36 (1.02) vs 0.43 (0.80), p=NR; 8 mo: 0.45 (0.76) vs 0.47 (0.95), p=NR; 9 mo: 0.36 (0.93) vs 0.40 (0.90), p=NR; 10 mo: 0.48 (0.86) vs 0.50 (0.90), p=NR; 11 mo: 0.38 (0.91) vs 0.34 (0.76), p=NR; 12 mo: 0.55 (0.81) vs 0.49 (0.79), p=NR; [underlined: WAZ @ 5 mo - 12 mo (Mean (SD))]; Meat vs Dairy; Group x time interaction: p=0.49; 5 mo: −0.03 (0.69) vs −0.14 (0.82), p=NS; 7 mo: 0.13 (0.64) vs 0.10 (0.72), p=NS; 8 mo: 0.26 (0.71) vs 0.13 (0.72), p=NS; 9 mo: 0.28 (0.69) vs 0.26 (0.70), p=NS; 10 mo: 0.35 (0.66) vs 0.30 (0.71), p=NS; 11 mo: 0.43 (0.66) vs 0.33 (0.69), p=NS; 12 mo: 0.40 (0.74) vs 0.39 (0.78), p=NS; [underlined: LAZ @ 5 mo - 12 mo (Mean (SD))]; Meat vs Dairy; Group x time interaction: p=0.00001; 5 mo: −0.19 (0.86) vs −0.30 (1.02), p=NS; 7 mo: −0.14 (1.02) vs −0.44 (0.98), p=NS; 8 mo: −0.19 (0.88) vs −0.58 (1.00), p=NS; 9 mo: −0.12 (0.86) vs −0.62 (1.10), p<0.05; 10 mo: −0.07 (0.91) vs −0.62 (1.02), p<0.05; 11 mo: −0.05 (0.91) vs −0.69 (1.01), p<0.05; 12 mo: 0.14 (0.90) vs −0.60 (0.91), p=0.001; [underlined: WLZ @ 5 mo - 12 mo (Mean (SD))]; Meat vs Dairy; Group x time interaction: p=0.015; 5 mo: 0.18 (0.73) vs 0.16 (0.88), p=NS; 7 mo: 0.40 (0.79) vs 0.55 (0.95), p=NS; 8 mo: 0.57 (0.84) vs 0.68 (0.94), p=NS; 9 mo: 0.51 (0.78) vs 0.82 (0.96), p=NS; 10 mo: 0.53 (0.80) vs 0.84 (0.98), p=NS; 11 mo: 0.63 (0.68) vs 0.88 (0.88), p=0.03; 12 mo: 0.48 (0.75) vs 0.92 (0.88), p=0.03 | [underlined: Model adjustments:] None (participants matched by sex and race/ethnicity); [underlined: Funding:] NIH (NIDDK); NIH/National Center for Advancing Translational Sciences Colorado Clinical and Translational Science Awards; Abbott Nutrition; American Heart Association; the Beef Checkoff (National Cattlemen's Beef Association); Leprino Foods; National Pork Board.
Tang, 2019 (https://pubmed.ncbi.nlm.nih.gov/30413312/)^46^; RCT-Parallel, U.S.; [underlined: Analytic N by group:] Meat: n=27, Dairy: n=26; [underlined: Attrition:] Meat: 23%; Dairy: 28% (Excluded participants who moved, were not compliant, switched formula, or lost contact); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race/ethnicity:] NR; [underlined: Maternal education:] NR; [underlined: Other SEP measure(s):] NR; [underlined: Maternal age:] ~30 y; [underlined: Milk feeding practices:] 100% exclusively formula-fed infants; [underlined: Child sex (female):] ~53%; [underlined: Birth weight:] ~3.3 kg; [underlined: Gestational age:] ~39 wk | [underlined: Intervention(s):] Meat-based complementary foods (pureed meats) from 5 mo to 12 mo of age in addition to infant formula (same formula given to both groups). (Total protein intake, including formula, ~3g/kg/d.) Fruit and vegetable intake not restricted.; [underlined: Comparator(s):] Dairy-based complementary foods (infant yogurt, cheese, powdered concentrate of 80% whey protein) from 5 mo to 12 mo of age in addition to infant formula (same formula given to both groups). (Total protein intake, including formula, ~3g/kg/d.) Fruit and vegetable intake not restricted.; [underlined: Dietary assessment methods:] Parental report via calendars to record daily consumption, 3-d diet records completed monthly. Return of unused foods, if any.; [underlined: Compliance:] >90% of protein from solid foods was from the assigned protein group (meat or dairy); <5% was from the alternative; [underlined: Age at intervention:] 5–12 mo; [underlined: Intervention duration:] 7 mo; [underlined: Outcome(s):] Weight, Length, WAZ, LAZ, WLZ; [underlined: Outcome assessment methods:] Length and weight measured by blinded, trained research personnel.; [underlined: Age(s) at outcome assessment:] 24 mo | [underlined: Weight (kg) @ 24 mo (Mean (SD))]; Meat vs Dairy; 12.6 (1.0) vs 12.4 (1.5), p=0.38; [underlined: Length (cm) @ 24 mo (Mean (SD))]; Meat vs Dairy; 89.0 (2.3) vs 87.1 (3.3), p=0.02; [underlined: WAZ @ 24 mo (Mean (SD))]; Data NR, p=0.65; [underlined: LAZ @ 24 mo (Mean (SD))]; Meat vs Dairy; 12 mo: 75.7 (2.6) vs 73.9 (2.2), p=NR; [underlined: WLZ @ 24 mo (Mean (SD))]; Data NR, p=0.40 | [underlined: Model adjustments:] NA (participants matched by sex and race/ethnicity); [underlined: Funding:] NIH (NIDDK); NIH/National Center for Advancing Translational Sciences Colorado Clinical and Translational Science Awards; Abbott Nutrition; American Heart Association; the Beef Checkoff (National Cattlemen's Beef Association); Leprino Foods; National Pork Board
Cluster-RCT
Ma, 2016 (https://pubmed.ncbi.nlm.nih.gov/27923057/)^39^; RCT-Cluster, China; [underlined: Analytic N by group:] Meat: n=137 (20 clusters); Fortified cereal: n=140 (20 clusters); Local cereal: n=133 (20 clusters); [underlined: Attrition:] NA for sub-samples (attrition before sub-sample identified: Meat: 10%, Fortified cereal: 10%, Local cereal: 14%) (Excluded participants who were lost to follow-up or who were not randomly selected for the sub-sample for blood collection and analysis.); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race/ethnicity:] NR; [underlined: Maternal education:] NR; [underlined: Other SEP measure(s):] NR; [underlined: Maternal age:] NR; [underlined: Milk feeding practices:] 100% EBF at enrollment (5 mo); [underlined: Child sex (female):] 48%; [underlined: Birth weight:] 100% >2,000 g; [underlined: Gestational age:] 100% with term delivery (37–42 wk) | [underlined: Intervention(s):] Meat: Minced fresh, certified safe pork to be boiled and served daily (50 g); [underlined: Comparator(s):] Fortified cereal: Commercially available fortified cereal (Fe, Zn, vitamin B12); Local cereal: isocaloric local cereal (made of glutinous rice flour, white granulated sugar, and honey).; [underlined: Dietary assessment methods:] Consumption checked and recorded by community doctors biweekly (meat) or weekly (cereal); [underlined: Compliance:] NR; [underlined: Age at intervention:] 6 mo to 18 mo; [underlined: Intervention duration:] 12 mo; [underlined: Outcome(s):] LAZ, WAZ, WLZ; [underlined: Outcome assessment methods:] Length and weight measured by trained study personnel. Z scores calculated using 2006 WHO Child Growth Standards; [underlined: Age(s) at outcome assessment:] 6, 12, and 18 mo | [underlined: LAZ @ 18 mo (mean (SD))]; Meat vs Fortified cereal vs Local cereal; −1.47 (0.99) vs −1.83 (0.95) vs −1.67 (0.97), p=0.024 (Meat vs Fortified cereal, p<0.05); [underlined: Change in LAZ from 6 to 18 mo (mean (SD))]; Meat vs Fortified cereal vs Local cereal; −0.41 (0.78) vs −0.71 (0.64) vs −0.62 (0.75), p=0.021 (Meat vs Local cereal and Meat vs; Fortified cereal, p<0.05); [underlined: WAZ @ 18 mo (mean (SD))]; Meat vs Fortified cereal vs Local cereal; −0.89 (0.93) vs −1.04 (0.89) vs −0.91 (0.88), p=0.496; [underlined: Change in WAZ @ 6–18 mo (mean (SD))]; Meat vs Fortified cereal vs Local cereal; −0.42 (0.61) vs −0.43 (0.58) vs −0.34 (0.73), p=0.872; [underlined: WLZ @ 18 mo (mean (SD))]; Meat vs Fortified cereal vs Local cereal; −0.27 (0.92) vs −0.24 (0.84) vs −0.15 (0.82), p=0.507; [underlined: Change in WLZ @ 6–18 mo (mean (SD))]; Meat vs Fortified cereal vs Local cereal; −0.61 (0.90) vs −0.44 (0.78) vs −0.36 (0.86), p=0.114 | [underlined: Model adjustments:] sex, birth weight, mother's pre-pregnancy BMI; [underlined: Funding:] National Natural Science Foundation of China, Thrasher Foundation
Tang, 2014 (https://pubmed.ncbi.nlm.nih.gov/25639137/)^41^; RCT-Cluster, China; [underlined: Analytic N by group:] Meat: n=462 (20 clusters), Cereal: n=856 (40 clusters); [underlined: Attrition:] Meat: 10%; Cereal: 11% (Reasons for attrition NR); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race/ethnicity:] Chinese: 100%; [underlined: Maternal education:] ≥9 y education: ~55%; [underlined: Other SEP measure(s):] Paid work: ~7%; [underlined: Maternal age:] NR; [underlined: Milk feeding practices:] 100% EBF at 6 mo (enrollment); [underlined: Child sex (female):] NR; [underlined: Birth size:] NR; [underlined: Gestational age:] 100% with term delivery | [underlined: Intervention(s):] Meat: Minced fresh, certified safe pork to be boiled and served daily (60 g); [underlined: Comparator(s):] Cereal: Commercially available or isocaloric packaged pressed rice cereal product produced locally; [underlined: Dietary assessment methods:] Weekly histories and observation of feeding; [underlined: Compliance:] NR; [underlined: Age at intervention:] 6 mo to 18 mo; [underlined: Intervention duration:] 12 mo; [underlined: Outcome(s):] Length, weight, HC, LAZ, WAZ, WLZ, HCZ; [underlined: Outcome assessment methods:] Length, weight, and HC measured by trained study personnel. Z scores calculated using WHO standards.; [underlined: Age(s) at outcome assessment:] 6, 7, 9, 12, 15, and 18 mo | [underlined: Change in length (cm) from 6 to 18 mo (mean (SD))]; Meat vs Cereal: 13.01 (1.9) vs 12.75 (1.8), p=0.01; [underlined: Change in LAZ from 6 to 18 mo (mean (SD))]; Meat vs Cereal:−0.43 (0.72) vs −0.54 (0.67), p<0.01; [underlined: Change in weight (kg) from 6 to 18 mo (mean (SD))]; Meat vs Cereal: 2.45 (0.60) vs 2.38 (0.60), p=0.08; [underlined: Change in WAZ from 6 to 18 mo (mean (SD))] Meat vs Cereal: −0.35 (0.60) vs −0.43 (0.61), p=0.05; [underlined: Change in WLZ from 6 to 18 mo (mean (SD))] Meat vs Cereal: −0.47 (0.79) vs −0.50 (0.81), p=0.62; [underlined: Change in HC (cm) from 6 to 18 mo (mean (SD))]; Meat vs Cereal: 3.80 (0.73) vs 3.82 (0.65), p=0.66; [underlined: Change in HCZ from 6 to 18 mo (mean (SD))] Meat vs Cereal: −0.19 (0.56) vs −0.18 (0.50), p=0.87 | [underlined: Model adjustments:] Baseline length, baseline LAZ, maternal education, work status, maternal height and weight; [underlined: Funding:] Thrasher Foundation; Science and Technology Commission of Shanghai Municipality; National Natural Science Foundation of China; Shanghai Key Laboratory of Pediatric Gastroenterology and Nutrition; NIH
PCS
Amaro-Rivera, 2019 (https://pubmed.ncbi.nlm.nih.gov/31260549/)^1^; PCS, U.S. (Puerto Rico); [underlined: Analytic N] = 68 (Excluded participants lost to follow-up); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race/ethnicity:] Hispanic: 100%; [underlined: Maternal education:] ≤HS: 32.5%, >HS: 67.5%; [underlined: Other SEP measure(s):] WIC participation: 100%; [underlined: Maternal age:] Parent’s age: <30 y: 55.8%, ≥30 y: 44.2%; [underlined: Milk feeding practices:] EBF for ≥1 mo: 51%, Ever FF: 70.1%, Any BF at ~10 mo: 20.8%; [underlined: Child sex (female):] 47%; [underlined: Birth size:] NR; [underlined: Gestational age:] NR | [underlined: Exposure(s) and comparator(s):] Annual change (amounts) in proteins Diet Quality Index Scores (continuous); [underlined: Dietary assessment methods:] Interviewer-administered questionnaire completed by caregivers. Diet Quality Index Score based on FFQ.; [underlined: Age(s) at dietary assessment:] 0–5, 8–36 mo (types/amounts); [underlined: Amounts consumed:] NR; [underlined: Outcome(s):] WLZ (≥1); [underlined: Outcome assessment methods:] Weight and length measured by trained research staff. Weight status assessed using WHO age- and sex-specific WLZ growth charts. Relative risk for WLZ (≥1 z-score vs <1 z-score), with underweight defined as WLZ ≤- 2 SD, healthy weight status defined as WLZ >-2 and <1 SD, risk of overweight defined as WLZ between 1-<2, and overweight or obesity defined as WLZ ≥2 SD.; [underlined: Age(s) at outcome assessment:] 11–36 mo (Median: 21 mo, 11–23 mo: 61.0%, 24–36 mo: 39.0%) | [underlined: WLZ (≥1 vs <1) @ 11–36 mo (RR (95% CI))]; Proteins score: 1.05 (0.92, 1.20) | [underlined: Key confounders accounted for:] SEP; sex; race and/or ethnicity; milk feeding practices; baseline anthropometry; [underlined: Key confounders NOT accounted for:] gestational age; [underlined: Model adjustments:] WLZ at baseline; [underlined: Funding:] University of Puerto Rico Central Administration Grant; Capacity Advancement in Research Infrastructure; NIMHD
Duchen, 2020 (https://pubmed.ncbi.nlm.nih.gov/32128243/)^43^; PCS, ABIS, Sweden; [underlined: Analytic N] = 6,749 (5 y), 3,017 (8 y) (Excluded participants lost to follow-up, twin siblings, children with body height outside the normal distribution (+/− 2 SD), and children with body weight <-2 SD or >6 SD); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race/ethnicity:] Both parents Swedish: ~91%, One parent not Swedish: ~7%, Both parents born abroad: ~2%; [underlined: Maternal education:] Primary school: ~6%, Secondary school: ~59%, College/university: ~35%; [underlined: Other SEP measure(s):] Paternal education: Primary school: ~12%, Secondary school: ~62%, College/university: ~26%; Disposable household income: Low (20%): ~16%, Medium (60%): ~41%, High (20%): ~43%; [underlined: Maternal age:] ~30 y; Milk feeding practices: Partial BF: ~7 mo, EBF: ~4.5 mo; [underlined: Child sex (female):] 48%; [underlined: Birth weight:] ~3,600 g; [underlined: Birth length:] ~51 cm,; [underlined: Appropriate for gestational age:] ~93%; [underlined: Gestational age:] ~40 wk | [underlined: Exposure(s) and comparator(s):] Fatty-fish index: <1 x/wk, 1–2 x/wk, 3–5 x/wk, daily or almost daily; [underlined: Dietary assessment methods:] FFQ; [underlined: Age(s) at dietary assessment:] 1 y; [underlined: Amounts consumed:] Fatty fish intake at 1 y: Seldom: ~89%, 1–2 x/wk: ~10%, 3–5 x/wk / almost daily: ~1%; [underlined: Outcome(s):] Weight status; [underlined: Outcome assessment methods:] Weight and height reported by parents and validated between health clinic charts at 5 y. Age and sex specific BMI calculated using international standards; used to divide participants into 4 categories (underweight, normal weight, overweight, obesity); [underlined: Age(s) at outcome assessment:] 5 y, 8 y | [underlined: Weight status @ 5 y, 8 y (t value)]; @ 5 y: 1.18, p=0.24; @ 8 y: 1.07, p=0.29 | [underlined: Key confounders accounted for:] SEP; sex; milk feeding practices; [underlined: Key confounders NOT accounted for:] race and/or ethnicity; gestational age; baseline anthropometry; [underlined: Model adjustments:] Sex, maternal BMI, birth weight, maternal nutritional quality during pregnancy, mother smoking during pregnancy, mother's education, serious life events before the child is 5 y/8 y, physical activity at 5 y/8 y, TV watching at 5 y/8 y; 5 y only: size for gestational age, BF duration, fatty fish consumption at 2.5 y, psychosocial vulnerability in the family, household income; [underlined: Funding:] The Ekhaga Foundation, The Swedish Research Council Formas, The Research Council for the South-East of Sweden, The Östergötland County Council, and The Swedish Asthma and Allergy Research Foundation, The Swedish Research Council, and Trygg Hansa Research Foundation
Garden, 2011 (https://pubmed.ncbi.nlm.nih.gov/21346718/)^30^; PCS, CAPS, Australia; [underlined: Analytic N] = 362 (Excluded participants with missing data on diet or anthropometrics); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race/ethnicity:] Grandparents ethnicity/country of birth: Caucasian: 55%, European: 9%, Middle Eastern: 4%, Indian: 5%, Asian: 4%, Undefined: 24%; [underlined: Maternal education:] NR; [underlined: Other SEP measure(s):] Paternal education: ≤10 y: 33%, 11–12 y: 18%, Tertiary education: 48%; [underlined: Maternal age:] NR; [underlined: Milk feeding practices:] BF ≥6 mo: 42%; [underlined: Child sex (female):] 49%; [underlined: Birth weight:] 3,493 (492) g; [underlined: Gestational age:] NR; [underlined: Other relevant characteristics:] Secondary analysis of RCT (testing intervention of house dust mite avoidance and omega-3 supplementation); all children recruited at increased risk of developing asthma | [underlined: Exposure(s) and comparator(s):] Continuous (amounts; as tertiles, quartiles, or quintiles): Meats; [underlined: Dietary assessment methods:] 3-d weighed food records; [underlined: Age(s) at dietary assessment:] 18 mo; [underlined: Amounts consumed:] Quintiles of grams (g); % total energy intake; Meats: 0, 9, 21, 34, 53; 0, 2, 4, 7, 11; [underlined: Outcome(s):] BMI, waist circumference; [underlined: Outcome assessment methods:] Weight, length, and waist circumference measured by study nurses; [underlined: Age(s) at outcome assessment:] 8 y | [underlined: BMI @ 8 y (β (95% CI))]; Meats, per quintile; g: 0.25 (0.04, 0.45), p for trend=0.02; % of total energy: 0.27 (0.07, 0.47), p for trend=0.01; [underlined: WC (cm) @ 8 y (β (95% CI))]; Meats, per quintile; g: 0.59 (0.03, 1.15), p for trend=0.04; % of total energy: 0.63 (0.10, 1.17), p for trend=0.02 | [underlined: Key confounders accounted for:] SEP; sex; race and/or ethnicity; milk feeding practices; gestational age; [underlined: Key confounders NOT accounted for:] baseline anthropometry; [underlined: Model adjustments:] sex, asthma study intervention group, birth weight, breastfeeding for at least 6 months, parental obesity status, ethnicity, smoking in pregnancy and father’s education, total energy intake (food intake in grams only); [underlined: Funding:] The National Health and Medical Research Council of Australia; Cooperative Research Centre for Asthma; New South Wales Department of Health; Children’s Hospital Westmead; University of Sydney, Faculty of Medicine; Commonwealth Department of Health and Aging
Garden, 2012 (https://pubmed.ncbi.nlm.nih.gov/23201761/)^29^; PCS, CAPS, Australia; [underlined: Analytic N] = 298 (Excluded participants who were not still participating in the study at 11.5 y or did not have dietary data.); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race/ethnicity:] NR (Australian born mother 74%, Australian born father: 69%; Child's grandparents ethnicity/country of birth: Caucasian: ~54%, European: ~9%, Middle Eastern/Indian/Asian: ~12%, Undefined: ~25%); [underlined: Maternal education:] 52% tertiary educated; [underlined: Other SEP measure(s):] Full-time employment: Mother: 49%, Father: 87%; [underlined: Maternal age:] 29.0 (5.1) y; [underlined: Milk feeding practices:] BF duration: 0 to <3 mo: 40%, 3 to <6 mo: 16.8%, ≥6 mo: 43.2%; [underlined: Child sex (female):] 49%; [underlined: Birth weight:] 100% ≥2.5 kg; [underlined: Gestational age:] 100% ≥36 wk; [underlined: Other relevant characteristics:] Secondary analysis of RCT (testing intervention of house dust mite avoidance and omega-3 supplementation); all children recruited at increased risk of developing asthma | [underlined: Exposure(s) and comparator(s):] Intake (amount) at 18 mo (all continuous): Meats; [underlined: Dietary assessment methods:] Parent/caregiver completed 3-d weighed food record (2 weekdays and 1 weekend day); [underlined: Age(s) at dietary assessment:] 18 mo (types and amounts); [underlined: Amounts consumed:] See results for intake data; [underlined: Outcome(s):] BMI trajectory; [underlined: Outcome assessment methods:] Weight and height measured by study nurses. Three BMI trajectories defined using latent basis growth mixture model in relationship to CDC percentiles, stratified by sex.; [underlined: Age(s) at outcome assessment:] 1, 3, 6, 9, 12, 18 mo, 2–5 y (every 6 mo), 8 y, 11.5 y | [underlined: BMI trajectory @ birth-11.5 y (OR (95% CI))]; Boys: Early and persistent BMI class vs normal BMI class (ref): 2.0 (1.2, 3.4); [underlined: BMI trajectory @ birth-11.5 y (median intake at 18 mo by trajectory group)]; Boys: normal trajectory: 18.6 g, early and persistent trajectory: 38.8 g, late BMI increase: 24.1 g, p=0.01; Girls: normal trajectory: 26.4 g, early and persistent trajectory: 25.4 g, late BMI increase: 35.0 g, p=0.57; Results analyzed by % of total energy were similar. | [underlined: Key confounders accounted for:] SEP; sex; race and/or ethnicity; milk feeding practices; baseline anthropometry (multinomial regression only).; [underlined: Key confounders NOT accounted for:] gestational age; [underlined: Model adjustments:] dietary intervention group, BF, parental obesity, ethnicity, smoking during pregnancy, father's education status (multinomial regression only); [underlined: Funding:] National Health and Medical Research Council of Australia
Jin, 2022 (https://pubmed.ncbi.nlm.nih.gov/34412548/)^31^; PCS, LoTiS, China; [underlined: Analytic N] = 302 (Excluded participants los to follow-up); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race/ethnicity:] NR; [underlined: Maternal education:] NR; [underlined: Other SEP measure(s):] NR; [underlined: Maternal age:] 30.47 (3.70) y; [underlined: Milk feeding practices:] BF duration: 7.60 (3.99) mo; Milk feeding at 12 mo: EBF: 4.6%, Exclusive formula feeding: 73.7%, Mixed breast and formula feeding: 21.7%; [underlined: Child sex (female):] 45%; [underlined: Birth weight:] 2.49 (0.45) kg;; [underlined: Birth length:] 46.04 (2.40) cm;; [underlined: SGA at birth:] 12.4%; [underlined: Gestational age:] 36.43 (1.48) wk; 53.2% born preterm; [underlined: Other relevant characteristics:] 100% twins (both included in analyses) | [underlined: Exposure(s) and comparator(s):] Meats: Continuous (frequency); [underlined: Dietary assessment methods:] FFQ completed by mother/guardian; [underlined: Age(s) at dietary assessment:] 12 mo; [underlined: Amounts consumed:] NR; [underlined: Outcome(s):] WAZ, HAZ, BMIZ, percent body fat mass, weight increment (12–24 mo), length increment (12–24 mo), BMI increment (12–24 mo); [underlined: Outcome assessment methods:] Weight and height were measured by study personnel. Z-scores calculated using WHO growth standards. Body fat was measured using bioimpedance.; [underlined: Age(s) at outcome assessment:] 12, 24 mo | [underlined: WAZ @ 24 mo (spearman correlation)]; Meats: 0.018, p=0.758; [underlined: HAZ @ 24 mo (spearman correlation)]; Meats: –0.026, p=0.653; [underlined: BMIZ @ 24 mo (spearman correlation)]; Meats: 0.058, p=0.312; [underlined: Weight increment from 12 to 24 mo (spearman correlation)]; Meats: 0.112, p=0.052; [underlined: Length increment from 12 to 24 mo (spearman correlation)]; Meats: 0.047, p=0.413; [underlined: BMI increment from 12 to 24 mo (spearman correlation)]; Meats: –0.057, p=0.357; [underlined: Body fat mass @ 24 mo (statistical measure NR, general linear model)]; Meats: 0.070, p=0.384; [underlined: Body fat percentage @ 24 mo (statistical measure NR, general linear model)] Meats: 0.034, p=0.669 | [underlined: Key confounders accounted for:] sex; baseline anthropometry (growth increments only); [underlined: Key confounders NOT accounted for:] SEP; race and/or ethnicity; milk feeding practices; gestational age; baseline anthropometry (WAZ, HAZ, BMIZ, body fat mass, body fat percentage); [underlined: Model adjustments:] sex (body fat mass, % body fat mass); None (all other outcomes); [underlined: Funding:] National Key Research and Development Program of China; National Natural Science Foundation of China; Chongqing Joint Program of Science and Health; Key Disciplines of Medical and Health Research of Yuhang District of Hangzhou City
Mahoney, 2018 (https://pubmed.ncbi.nlm.nih.gov/29607793/)^27^; PCS, Born in Bradford 1000, U.K.; [underlined: Analytic N] = 12 mo: 722; 18 mo: 779 (Excluded participants with multiple births, missing child dietary data or outcome data, and not of White British or Pakistani ethnicity); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race/ethnicity:] Pakistani: 56%, White British: 44%; [underlined: Maternal education:] NR; [underlined: Other SEP measure(s):] NR; [underlined: Maternal age:] NR; [underlined: Milk feeding practices:] NR; [underlined: Child sex (female):] NR; [underlined: Birth weight:] 3,234.15 (521.97) g; [underlined: Gestational age:] NR | [underlined: Exposure(s) and comparator(s):]; Processed meat products (≤ vs > Median frequency); [underlined: Dietary assessment methods:] FFQ completed by parents; [underlined: Age(s) at dietary assessment:] 12, 18 mo; [underlined: Amounts consumed:] Frequency at 12, 18 mo, respectively (Median, IQR): Processed meat products: 0.5 (0.0, 2.0) x/wk, 7.0 (0.0, 21.0) x/wk; Outcome(s): BMIZ; [underlined: Outcome assessment methods:] Height, weight measured by trained researchers. Age- and sex-adjusted BMI calculated based on WHO 2006 standards.; [underlined: Age(s) at outcome assessment:] 36 mo | [underlined: BMIZ @ 36 mo (β (95% CI))]; Intake @ 12 mo: > vs ≤ 0.5/wk: 0.01 (−0.16, 0.19), p=0.88; Intake @ 18 mo: > vs ≤ 7.0/wk: 0.00 (−0.19, 0.18), p=0.97 | [underlined: Key confounders accounted for:] Sex; race and/or ethnicity; baseline anthropometry; [underlined: Key confounders NOT accounted for:] SEP; milk feeding practices; gestational age; [underlined: Model adjustments:] Ethnicity, sex, birth weight, other key indicator food groups (formula milk; commercial savoury baby foods; commercial sweet baby foods; chips, roast and potato shapes; processed meat products; vegetables; fruit; cakes, biscuits, chocolate and sweets; crisps and savoury snacks; sugar-sweetened drinks; pure fruit juice; low-sugar drinks; water); [underlined: Funding:] NIHR
Morgan, 2004 (https://pubmed.ncbi.nlm.nih.gov/15572888/)^44^; PCS, U.K.; [underlined: Analytic N] = 134 (Reasons for exclusion NR); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race/ethnicity:] White: 97%, Caribbean, Indian, Chinese: 3%; [underlined: Maternal education:] NR; [underlined: Other SEP measure(s):] Social classification: Higher occupations: 39.9%, Intermediate: 36.4%, Lower: 11.1%, Never worked/long-term unemployed: 6.1%; [underlined: Maternal age:] 31–40 y: 64%; [underlined: Milk feeding practices:] BF at birth: 83%, BF at 4 mo: 37%, BF at 6 mo: 2%; [underlined: Child sex (female):] 47%; [underlined: Birth weight:] 100% >2500 g; [underlined: Gestational age:] 100% full-term | [underlined: Exposure(s) and comparator(s):] Total red and white meat intake (g) (sum of each 7-d food diary; continuous): 4–12 mo, 4–16 mo, 4–24 mo; [underlined: Dietary assessment methods:] 7-d weighed food diaries; [underlined: Age(s) at dietary assessment:] 4, 8, 12, 16, 20, and 24 mo; [underlined: Amounts consumed:] 4–12 mo (median (25th percentile, 75th percentile)): BF<6 wk or FF: 283 (183, 453) g/21 d period, BF≥6 wk: 265 (174, 370) g/21 d period; 4–16 mo: NR; 4–24 mo (median (25th percentile, 75th percentile)): 278 (178–425) g/42 d (~7 g/d); [underlined: Outcome(s):] Weight, length, HC; [underlined: Outcome assessment methods:] Weight, length, and head circumference measured by study personnel; [underlined: Age(s) at outcome assessment:] 4, 8, 12, 16, 20 and 24 mo | [underlined: Weight @ 12, 16, 24 mo]; @12 mo: Meat intake 4–12 mo: Data NR, p=NS @ 16 mo: Meat intake 4–16 mo: Data NR, p=NS @ 24 mo: Meat intake 4–24 mo: Data NR, p=NS; [underlined: Length @ 12, 16, 24 mo]; @ 12 mo: Meat intake 4–12 mo: Data NR, p=NS @ 16 mo: Meat intake 4–16 mo: Data NR, p=NS @ 24 mo: Meat intake 4–24 mo: Data NR, p=NS; [underlined: HC @ 12, 16, 24 mo]; @ 12 mo: Meat intake 4–12 mo: Data NR, p=NS @ 16 mo: Meat intake 4–16 mo: Data NR, p=NS @ 24 mo: Meat intake 4–24 mo: Data NR, p=NS | [underlined: Key confounders accounted for:] milk feeding practices; [underlined: Key confounders NOT accounted for:] SEP; sex; race and/or ethnicity; gestational age; baseline anthropometry; [underlined: Model adjustments:] BF, energy intake, protein intake, birth weight; [underlined: Funding:] University of Surrey, Royal Surrey County Hospital NHS Trust, the Medical Research Council, the Meat and Livestock Commission
Smith-Brown, 2018 (https://pubmed.ncbi.nlm.nih.gov/29493037/)^45^; PCS, Feeding Queensland Babies Study Cohort, Australia; [underlined: Analytic N] = 25 (Reasons for exclusion NR); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race/ethnicity:] NR; [underlined: Maternal education:] NR; [underlined: Other SEP measure(s):] NR; [underlined: Maternal age:] NR; [underlined: Milk feeding practices:] NR; [underlined: Child sex (female):] 44%; [underlined: Birth size:] NR; [underlined: Gestational age:] NR | [underlined: Exposure(s) and comparator(s):] Meat, fish, and egg (continuous; daily feedings); Animal protein foods (meat, fish, egg, and dairy; continuous; daily feedings); [underlined: Dietary assessment methods:] 18-item FFQ; [underlined: Age(s) at dietary assessment:] 12 mo; [underlined: Amounts consumed:] Meat, fish, and egg at 12 mo: 1.36 (0.64) daily feedings (Range: 0.00–2.43)*; Animal protein foods at 12 mo: 1.36 (0.64) daily feedings (Range: 0.00–2.43)*; *Possible reporting error; [underlined: Outcome(s):] FMI, FFMI, WHR, BMIZ; [underlined: Outcome assessment methods:] Weight, height, and WC were measured by study personnel. Fat mass and fat free mass were measured using total body water (deuterium oxide dilution technique) converted to age- and sex-specific hydration constants. FMI and FFMI calculated by dividing fat-free/fat mass by square of height. BMIZ calculated using WHO reference data. WHR, FFMI, and FMI z-scores calculated using values calculated from NHANES.; [underlined: Age(s) at outcome assessment:] 2–3 y (Mean: 2.65 y) | [underlined: BMIZ @ 2–3 y (Pearson's correlation)]; Animal protein food (dairy and meat, fish, and egg): r=0.35, p=0.061; Meat, fish, and egg: r=0.39, p=0.086; [underlined: FMI Z-score @ 2–3 y (Pearson's correlation)] Animal protein food (dairy and meat, fish, and egg): r=−0.221, p=0.061; Meat, fish, and egg: r=−0.084, p=0.689; [underlined: FFMI Z-score @ 2–3 y (Pearson's correlation)]; Animal protein food (dairy and meat, fish, and egg): r=0.58, p=0.008; Meat, fish, and egg: r=0.53, p=0.021; [underlined: WHR Z-score @ 2–3 y (Pearson's correlation)] Animal protein food (dairy and meat, fish, and egg): r=0.37, p=0.061; Meat, fish, and egg: r=0.55, p=0.021 | [underlined: Key confounders accounted for:] None; [underlined: Key confounders NOT accounted for]: SEP; sex; race and/or ethnicity; milk feeding practices; gestational age; baseline anthropometry; [underlined: Model adjustments:] None; [underlined: Funding:] Australian government, Danone Nutricia

a Abbreviations: @: at; ABIS: All Children in South-East Sweden; AGA: appropriate for gestational age; ALA: alpha-linolenic acid; β: beta; BF: breastfeeding; BMI: body mass index; BMIZ: BMI z-score; CAPS: Childhood Asthma Prevention Study; CDC: Centers for Disease Control and Prevention; CI: confidence interval; cm: centimeter; d: day; EBF: exclusive breastfeeding; Fe: iron; FF: formula feeding; FFMI: fat-free mass index; FFQ: food-frequency questionnaire; FMI: fat mass index; g: gram; HAZ: height-for-age z-score; HC: head circumference; HCZ: head circumference z-score; kg: kilogram; LAZ: length-for-age z-score; LoTiS: Longitudinal Twin Study; mm: millimeter; mo: month; NHANES: National Health and Nutrition Examination Survey; NR: not reported; NS: non-significant; OR: odds ratio; PCS: prospective cohort study; PR: prevalence ratio; RCT: randomized controlled trial; RR: risk ratio; SD: standard deviation; SEP: socioeconomic position; SGA: small for gestational age; U.K: United Kingdom; U.S.: United States; vs: versus; WAZ: weight-for-age z-score; WC: waist circumference; WHO: World Health Organization; WHR: waist to height ratio; wk: week; WLZ: weight-for-length z-score; x: times; y: year; Zn: zinc

Table 45 Risk of bias for randomized controlled trials (parallel) examining consumption of protein foods and growth, body composition, and risk of obesity ^a^

Article | Randomization | Deviations from intended interventions (effect of assignment or per-protocol) | Missing outcome data | Outcome measurement | Selection of the reported result | Overall risk of bias
Krebs, 2006^35^ | SOME CONCERNS | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Tang, 2018^47^ | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS
Tang, 2019^46^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS

a Possible ratings of low, some concerns, or high determined using the "Cochrane Risk-of-bias 2.0" (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2019 version)” ( Sterne JAC, Savović J, Page MJ, Elbers RG, Blencowe NS, Boutron I, Cates CJ, Cheng H-Y, Corbett MS, Eldridge SM, Hernán MA, Hopewell S, Hróbjartsson A, Junqueira DR, Jüni P, Kirkham JJ, Lasserson T, Li T, McAleenan A, Reeves BC, Shepperd S, Shrier I, Stewart LA, Tilling K, White IR, Whiting PF, Higgins JPT. RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ 2019; 366: l4898.31462531

Table 46 Risk of bias for randomized controlled trials (cluster) examining consumption of protein foods and growth, body composition, and risk of obesity ^b^

Article | Randomization | Timing of identification and recruitment of individual participants in relation to timing of randomization | Deviations from the intended interventions (effect of assignment/adhering to intervention) | Missing outcome data | Outcome measurement | Selection of the reported result | Overall risk of bias
Ma, 2016^39^ | HIGH | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | HIGH
Tang, 2014^41^ | HIGH | SOME CONCERNS | LOW | LOW | LOW | LOW | HIGH

b Possible ratings of low, some concerns, or high determined using the "Cochrane Risk-of-bias 2.0" (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2019 version)” ( Sterne JAC, Savović J, Page MJ, Elbers RG, Blencowe NS, Boutron I, Cates CJ, Cheng H-Y, Corbett MS, Eldridge SM, Hernán MA, Hopewell S, Hróbjartsson A, Junqueira DR, Jüni P, Kirkham JJ, Lasserson T, Li T, McAleenan A, Reeves BC, Shepperd S, Shrier I, Stewart LA, Tilling K, White IR, Whiting PF, Higgins JPT. RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ 2019; 366: l4898.31462531

Table 47 Risk of bias for observational studies examining consumption of protein foods and growth, body composition, and risk of obesity ^a^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Amaro-Rivera, 2019 | SOME CONCERNS | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Duchen, 2019 | HIGH | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Garden, 2011 | SOME CONCERNS | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Garden, 2012 | SOME CONCERNS | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Jin, 2021 (BMIZ, HAZ, WAZ, growth increments) | VERY HIGH | SOME CONCERNS | LOW | LOW | LOW | LOW | HIGH | VERY HIGH
Jin, 2021 (body fat mass, % fat mass) | HIGH | SOME CONCERNS | LOW | LOW | LOW | LOW | HIGH | HIGH
Mahoney, 2018 | HIGH | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Morgan, 2004 | HIGH | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Smith-Brown, 2018 | VERY HIGH | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | VERY HIGH

a Possible ratings of low, some concerns, high, very high, no information, or not applicable determined using the "Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)" tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602. ) *Low risk of bias except for concerns about uncontrolled confounding.

### Dairy and fortified soy alternatives

#### Description of the evidence

Eleven studies (14 articles) met inclusion criteria and examined the relationship between the consumption of dairy by infants and young children, up to age 24 months, and growth, body composition, and risk of obesity (Table 49).^14,29,30,45–55^Three studies (4 articles) were parallel RCTs^46,47,52,54^ and 1 study (2 articles) was a non-randomized controlled trial (NRCT).^48,49^ Seven studies (8 articles) were PCS,^14,29,30,45,50,51,53,55^ using data from the following cohorts: the Bogalusa Heart Study,^14^ CAPS,^29,30^ the National Health Information Database,^50^ the Feeding Queensland Babies Study,^45^ the Child in Focus substudy of the Avon Longitudinal Study of Parents and Children,^51^ and 2 unnamed studies^53,55^ Two studies were secondary analyses of RCTs, 1 that tested the impact of dust mite avoidance and omega-3 fatty acid supplementation on asthma prevention^29,30^ and 1 that assessed the effect of different ages of introduction to solid food on growth and body composition.^55^

##### Population

The studies were conducted in a variety of countries including Australia,^29,30,45,5^4 Canada,^48,49^ Denmark,^52^ Iceland,^53^ Korea,^50^ New Zealand,^54^ the United Kingdom,^51^ and the United States.^14,46,47,55^ The analytic sample sizes primarily ranged from 25^45^ to 948 participants;^51^ however, 1 study based on data from a national health insurance service included 142,668 participants.^50^ All 3 RCTs reported being sufficiently powered to address an outcome related to growth, body composition, or risk of obesity,^46,47,52,54^ while the NRCT and PCS did not provide information related to statistical power.

Race and/or ethnicity was reported by approximately half of the studies. Across the 5 studies that did report this information, all reported that between 55% and 94% of participants were White, Caucasian, and/or were of European ancestry.^14,29,30,46,47,54,55^ Individuals of other races and/or ethnicities, such as individuals who were Black,^14,46,47^ Middle Eastern,^29,30^ Indian,^29,30^ Asian and/or Pacific Islander,^29,30,46,47,54^ and Hispanic,^46,47^ were represented across the studies but at much lower proportions. Average maternal age ranged from approximately age 27 to 31 years in the 4 studies that reported this information.^29,46,47,49,53^ One RCT was conducted with infants who were exclusively formula-fed at age 5 months,^46,47^ while the remaining studies with information on human milk and infant formula feeding reported a range of practices^14,29,30,48–53^ Regarding any breastfeeding, 1 study reported that the average duration was 8 months,^53^ while a second study noted that 42% of infants were breastfed for at least 6 months.^30^ Regarding exclusive breastfeeding, 1 study reported an average duration of 4 months,^53^ while a second study noted that 46% of participants were exclusively breastfed at age 4 to 6 months.^50^ Additionally, among some studies that examined cow’s milk as an exposure during infancy, those consuming cow’s milk were not consuming human milk.^14,48,49,51^ The most commonly reported measure of SEP was maternal education; the level of education attained varied across these studies,^29,49,51,53–55^ ranging from an average of approximately 5 years postprimary school^49^ to approximately 74% of participants with a tertiary education.^54^

Regarding the infants and young children, approximately 50% of the participants were female in individual studies and the average birth weight ranged from approximately 3.2 kilograms to 3.7 kilograms.^30,46,47,50–54^ Some studies did not report average birth weight, but indicated that all participants weighed at least 2.5 kilograms at birth^29,48,49^ or were not born small for gestational age (SGA).^55^ Most or all infants included in individual studies were born at term.^29,46–55^ One study found that baseline weight varied slightly between exposure groups,^14^ however, the remaining studies did not detect differences in baseline anthropometry between study groups,^47–49,52,55^ did not report testing for differences by intervention or exposure group,^30,51^ or did not report this information.^45,50,54^

##### Interventions/exposures and comparators

The studies that examined dairy primarily focused on cow’s milk,^14,29,30,48–55^ although some studies examined dairy products more broadly^29,30,45–47^ or examined alternatives to cow’s milk (i.e., soy and goat milk).^50^ The most common comparators were differing amounts or frequencies of dairy consumption,^14,29,30,48–54^ with infants and young children in the control or comparison groups often continuing to consume human milk or infant formula due to the age that the interventions occurred or the exposures that were assessed. Two RCTs compared dairy consumption to different foods or products: 1 compared dairy-based complementary foods to meat-based complementary foods,^46,47^ while 1 compared cow’s milk to “toddler milk”.^54^ Finally, 1 PCS compared consumption of 2% milk to whole milk.^55^ Among the PCS, most studies examined the exposures and comparators categorically, however 3 studies modeled dairy consumption continuously.^29,30,45,53^ Most of the studies examined consumption of dairy up to age 12 months,^14,46–53^, while 4 studies examined consumption of dairy from age 12 months up to age 24 months.^29,30,45,54,55^

##### Outcomes

Growth, body composition, and risk of obesity were assessed using a variety of outcomes. Outcomes related to growth were examined in all studies, with the most common measures including weight, length, WAZ, LAZ, WLZ, and BMIZ. Five studies examined body composition.^14,30,45,54,55^ Studies that reported z-scores, standard deviation scores (SDS), or percentiles primarily calculated these based on growth standards from the WHO^45–50,54^ or CDC,^29,46–49,55^ although 1 used reference data from the National Health and Nutrition Examination Survey (NHANES)^45^ and another used reference data from the United Kingdom.^51^ The outcomes were all measured by study personnel or medical staff. The age of the participants at outcome assessment ranged from age 3 months^49^ to age 11.5 years,^29^ with 7 studies measuring outcomes up to age 24 months,^14,46–49,51,52,54,55^ 4 studies measuring outcomes from age 2 to 10 years,^30,45,51,53^ and 2 studies examining growth trajectory or timing of adiposity rebound based on multiple measurements conducted up to age ^65^0 or 11.5 years.^29^

#### Synthesis of the evidence

Of the 11 studies that examined dairy consumption and outcomes related to growth, body composition, and risk of obesity, 8 reported mixed results,^29,30,45–51,53,54^ while 3 did not detect any statistically significant differences in outcomes by dairy consumption^14,52^ (Table 49).

One RCT,^52^ 1 NRCT,^48,49^ and 6 PCS^14,29,30,45,50,51,53^ examined differing amounts or frequencies of dairy consumption. First, the RCT did not detect an effect of whole cow’s milk consumption at age 9 months on either weight, length, or change in weight or length.^52^ Next, the NRCT, which examined infants consuming evaporated cow’s milk from early in infancy, found that weight gain velocity, change in WAZ, and head circumference growth velocity were greater from age 3 to 6 months, in addition to higher WAZ at age 18 months, compared to infants who continued to consume either human milk or infant formula; differences across other outcomes including WLZ/WHZ and LAZ were not detected.^48,49^ The PCS examined a wide range of exposures, comparators, and outcomes, and both the direction and statistical significance of findings varied.^14,29,30,45,50,51,53^ First, 3 studies detected direct associations between cow’s milk consumption between ages 8 to 12 months and measures including weight SDS,^51^ height SDS,^51^ BMI SDS,^51^ BMI,^53^ and odds of early adiposity rebound.^50^ Three additional studies examined cow’s milk consumption but did not detect any associations with a variety of outcomes including weight,^14^ length,^14^ BMI,^30^ BMI trajectory,^29^ waist circumference,^30^ and skinfold thickness.^14^ The differences in these outcomes by cow’s milk consumption were minimal and of variable direction.^14,29,30^ Despite all 6 studies having examined cow’s milk, there was still variability across comparators, with 2 comparing any to no consumption^14,50^ and 3 examining different amounts consumed.^29,30,51,53^ Further variability was observed in regard to the ages at which the exposures were measured, spanning from age 6 months through age 18 months. Few studies examined exposures other than cow’s milk, and the results were varied. Specifically, 1 study reported that dairy foods consumption at age 18 months was associated with lower BMI, but not waist circumference or BMI trajectory, during childhood,^29,30^ a second study reported that more frequent dairy consumption at age 12 months was positively correlated with fat-free mass index z-score at age 2 to 3 years, while correlations with other measures of body composition or growth were in a consistent direction, but weaker, and did not reach statistical significance,^45^ and a third study found that soy milk, but not goat’s milk, consumption at age 12 months was associated with greater odds of early adiposity rebound than infants continuing to consume human milk.^50^

Fewer studies compared consumption of dairy to another food or another type of dairy. Two RCTs found that infants randomized to consume dairy versus another product tended to show smaller increases or lower achieved length and LAZ during the intervention, but predominantly did not vary across a range of other measures related to growth such as BMIZ,^54^ WLZ,^54^ weight,^46,47,54^ WAZ,^46,47,54^ or head circumference.^47^ However, these studies varied considerably across a range of factors including the exposure (cow’s milk^54^ versus dairy-based complementary foods more broadly),^46,47^ the comparator (“toddler milk”^54^ versus meat),^46,47^ age at intervention (age 12 months^54^ versus age 5 months),^46,47^ and the time-point at which group differences were detected (mid-intervention^54^ versus end of intervention),^46,47^ limiting the comparability of these 2 trials. The RCT which compared consumption of cow’s milk to toddler milk also assessed body composition, reporting that infants consuming cow’s milk had higher body fat percentage, fat mass, and fat mass index by the end of the intervention, but did not differ in regard to fat-free mass, waist circumference or waist-to-height ratio.^54^ A final PCS compared consumption of cow’s milk with differing fat levels (2% versus whole), reporting no association between the fat level of cow’s milk consumed from age 12 months up to age 24 months and a variety of outcomes including length, LAZ, weight, WAZ, percent body fat, and fat mass during this time period.^55^

Although 11 studies assessed the relationship between dairy consumption and outcomes related to growth, body composition, and risk of obesity, the ability to draw conclusions from this body of evidence were limited by marked heterogeneity across the interventions and exposures, comparators, and outcomes as highlighted above. First, the age at which interventions were conducted or the exposures were measured varied greatly from birth up to age 24 months. For instance, while some studies examined dairy consumption, particularly cow’s milk, early in infancy, others examined dairy consumption at the upper range of this age group. Next, as previously noted, the comparators also varied widely across the studies: some compared dairy or cow’s milk consumption to consumption of different products such as meat or “toddler milk”, 1 study compared cow’s milks with different fat contents, and the remaining studies compared differing amounts of cow’s milk or dairy, including some with no consumption. For several of these studies, particularly those in which cow’s milk was examined during infancy, the comparison groups that had lower or no consumption of cow’s milk were continuing to consume either human milk or infant formula, further adding to the heterogeneity across studies Finally, the studies varied in the outcomes examined and the ages at which they were measured, ranging from age 6 months to age 11.5 years.

#### Conclusion statement and grade

The Committee did not draw a conclusion statement about the relationship between consumption of dairy by infants and young children, up to 24 months, and growth, body composition, and risk of obesity (Table 48). This was due to substantial concerns with consistency in the body of evidence. First, the age at which the interventions were conducted, or the exposures were measured, varied greatly from birth up to age 24 months. Next, the comparators also varied widely across the studies, inclusive of different foods, different fat contents, and different frequencies or amounts. Finally, the studies varied widely in the outcomes examined and the ages at which they were measured. Publication bias was also a consideration; however, this was not assessed as a serious concern because the body of evidence included studies that reported only nonsignificant findings as well as studies that reported a mix of both significant and nonsignificant results, across a range of analytic sample sizes. However, while the literature search was comprehensive, a search of the gray literature was not done, which could increase the possibility of publication bias. The risk of bias of the parallel RCTs, NRCT, and PCS are presented in Table 50, Table 51, and Table 52, respectively.

Table 48 Conclusion statement, grade for dairy consumption by infants and young children and growth, body composition, and risk of obesity

Conclusion Statement | A conclusion statement cannot be drawn about the relationship between dairy consumption by infants and young children, up to age 24 months, and outcomes related to growth patterns, body composition, and risk of obesity during childhood because of substantial concerns with consistency in the body of evidence.
Grade | Grade Not Assignable
Body of Evidence | 14 articles (11 studies): 3 randomized controlled trials (4 articles), 1 non-randomized controlled trial (2 articles), 7 prospective cohort studies (8 articles)
Rationale | The studies varied in the ages at intervention/exposure assessment, comparator, and the outcomes examined.

Table 49 Evidence examining the relationship between dairy consumption and growth, body composition, and risk of obesity ^a^

Study and Participant Characteristics | Intervention/Exposure, Comparator, and Outcome | Results | Key Confounders, Model Adjustments, Funding
RCT-Parallel
Larnkjaer, 2009 (https://pubmed.ncbi.nlm.nih.gov/19174829/)^52^; RCT-Parallel, Denmark; [underlined: Analytic N by group:] Whole milk: n=38, Infant formula: n=45; [underlined: Attrition:] Whole milk: 17%, Infant formula: 6% (Excluded participants who did not complete the study); [underlined: Adequately powered:] Yes; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race/ethnicity:] NR; [underlined: Maternal education:] NR; [underlined: Other SEP measure(s):] NR; [underlined: Maternal age:] NR; [underlined: Milk feeding practices:] Duration of full BF: ~4.2 mo; Any BF at 9–12 mo: whole milk: 57%, infant formula: 29%, p≤0.005; [underlined: Child sex (female):] 51%; [underlined: Birth weight:] ~3,664 g; [underlined: Gestational age:] 100% ≥37 wk; [underlined: Other relevant characteristics:] RCT used 2x2 factorial design (also examined fish oil supplementation) | [underlined: Intervention(s):] Whole milk: whole milk as primary milk source; those still breastfed continued to do so; [underlined: Comparator(s):] Infant formula: formula as the primary milk source; those still breastfed continued to do so; [underlined: Dietary assessment methods:] 7-d dietary record completed by parents; [underlined: Compliance:] Whole milk and whole milk products (g/d) at 12 mo: Whole milk group: 444 (200), Infant formula group: 97 (79), p<0.001; Infant formula (g/d) at 12 mo: Whole milk group: 17 (75), Infant formula group: 293 (151), p<0.001; [underlined: Age at intervention:] 9 mo; [underlined: Intervention duration:] 3 mo; [underlined: Outcome(s):] Weight, weight change, length, length change; [underlined: Outcome assessment methods:] Measured by research staff.; [underlined: Age(s) at outcome assessment:] 9, 12 mo | Whole milk vs Infant formula:; [underlined: Weight (g) @ 12 mo (Mean (SD))]; 9,823 (900) vs 10,021 (821), p=NS; [underlined: Weight change (g/mo) from 9 to 12 mo (Mean (SD))]; 257 (103) vs 242 (111), p=NS; [underlined: Length (cm) @ 12 mo (Mean (SD))]; 75.8 (2.2) vs 76.4 (2.2), p=NS; [underlined: Length change (cm/mo) from 9 to 12 mo (Mean (SD))]; 1.24 (0.28) vs 1.25 (0.34), p=NS | [underlined: Model adjustments:] Fish oil supplementation group, sex, baseline anthropometric value at 9 mo; [underlined: Funding:] Danish Research and Development Programme for Food and Technology
Tang, 2018 (https://pubmed.ncbi.nlm.nih.gov/29722841/)^47^; RCT-Parallel, U.S.; [underlined: Analytic N by group:] Meat: n=32, Dairy: n=32; [underlined: Attrition:] Meat: 8.6%, Dairy: 11.1% (Excluded participants who moved, were not compliant, switched formula, or lost contact); [underlined: Adequately powered:] Yes; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race/ethnicity:] White: ~75%, Hispanic: ~17.5%, Black: ~4.5%, Asian: ~3%; [underlined: Maternal education:] NR; [underlined: Other SEP measure(s):] NR; [underlined: Maternal age:] ~30 y; [underlined: Milk feeding practices:] 100% exclusively formula-fed infants; [underlined: Child sex (female):] ~53.5%; [underlined: Birth weight:] ~3.3 kg; [underlined: Gestational age:] ~39 wk | [underlined: Intervention(s):] Meat-based complementary foods (pureed beef, ham) from 5 mo to 12 mo of age in addition to infant formula (same formula given to both groups). (Total protein intake, including formula, ~3g/kg/d.) Fruit and vegetable intake not restricted.; [underlined: Comparator(s):] Dairy-based complementary foods (infant yogurt, cheese, powdered concentrate of 80% whey protein) from 5 mo to 12 mo of age in addition to infant formula (same formula given to both groups). (Total protein intake, including formula, ~3g/kg/d.) Fruit and vegetable intake not restricted.; [underlined: Dietary assessment methods:] Parental report via calendars to record daily consumption, 3-d diet records completed monthly. Return of unused foods, if any.; [underlined: Compliance:] Intervention: Protein from meat-based complementary foods at 10 mo −2.1 g/kg/d, Protein from dairy-based complementary foods at 10 mo −0.03 g/kg/d; Comparator: Protein from meat-based complementary foods at 10 mo −0.01 g/kg/d, Protein from dairy-based complementary foods at 10 mo −2.0 g/kg/d; [underlined: Age at intervention:] 5–12 mo; [underlined: Intervention duration:] 7 mo; [underlined: Outcome(s):] Weight, WAZ, Length, LAZ, WLZ, HC, HC Z-score; [underlined: Outcome assessment methods:] Length, weight, and head circumference measured by blinded, trained research personnel. Z-scores calculated using WHO/CDC growth standards.; [underlined: Age(s) at outcome assessment:] 5, 7, 8, 9, 10, 11, and 12 mo | [underlined: Weight (kg) @ 5 mo - 12 mo (Mean (SD))]; Group x time interaction: p=0.81; 5 mo: 7.37 (0.67) vs 7.35 (0.74), p=NS; 7 mo: 8.17 (0.70) vs 8.10 (0.77), p=NR; 8 mo: 8.63 (0.78) vs 8.49 (0.74), p=NR; 9 mo: 8.90 (0.75) vs 8.91 (0.75), p=NR; 10 mo: 9.28 (0.78) vs 9.23 (0.78), p=NR; 11 mo: 9.61 (0.81) vs 9.51 (0.79), p=NR; 12 mo: 9.92 (0.91) vs 9.92 (0.97), p=NR; [underlined: Length (cm) @ 5 mo - 12 mo (Mean (SD))]; Group x time interaction: p=0.0002; 5 mo: 65.3 (2.2) vs 65.3 (2.5), p=NS; 7 mo: 68.1 (2.7) vs 67.3 (2.2), p=NR; 8 mo: 69.5 (2.4) vs 68.5 (2.3), p=NR; 9 mo: 71.0 (2.3) vs 69.9 (2.5), p=NR; 10 mo: 72.5 (2.6) vs 71.2 (2.4), p=NR; 11 mo: 73.8 (2.6) vs 72.3 (2.3), p=NR; 12 mo: 75.7 (2.6) vs 73.9 (2.2), p=NR; [underlined: Head circumference (cm) @ 5 mo - 12 mo (Mean (SD))]; Group x time interaction: p=0.55; 5 mo: 43.0 (1.2) vs 43.1 (1.1), p=NS; 12 mo: 46.4 (1.3) vs 46.3 (1.1), p=NR; Head circumference (z-score) @ 5 mo - 12 mo (Mean (SD)); Group x time interaction: p=0.41; 5 mo: 0.51 (0.82) vs 0.54 (0.77), p=NS; 7 mo: 0.36 (1.02) vs 0.43 (0.80), p=NR; 8 mo: 0.45 (0.76) vs 0.47 (0.95), p=NR; 9 mo: 0.36 (0.93) vs 0.40 (0.90), p=NR; 10 mo: 0.48 (0.86) vs 0.50 (0.90), p=NR; 11 mo: 0.38 (0.91) vs 0.34 (0.76), p=NR; 12 mo: 0.55 (0.81) vs 0.49 (0.79), p=NR; [underlined: WAZ @ 5 mo - 12 mo (Mean (SD))]; Group x time interaction: p=0.49; 5 mo: −0.03 (0.69) vs −0.14 (0.82), p=NS; 7 mo: 0.13 (0.64) vs 0.10 (0.72), p=NS; 8 mo: 0.26 (0.71) vs 0.13 (0.72), p=NS; 9 mo: 0.28 (0.69) vs 0.26 (0.70), p=NS; 10 mo: 0.35 (0.66) vs 0.30 (0.71), p=NS; 11 mo: 0.43 (0.66) vs 0.33 (0.69), p=NS; 12 mo: 0.40 (0.74) vs 0.39 (0.78), p=NS; [underlined: LAZ @ 5 mo - 12 mo (Mean (SD))]; Group x time interaction: p=0.00001 5 mo: −0.19 (0.86) vs −0.30 (1.02), p=NS; 7 mo: −0.14 (1.02) vs −0.44 (0.98), p=NS; 8 mo: −0.19 (0.88) vs −0.58 (1.00), p=NS; 9 mo: −0.12 (0.86) vs −0.62 (1.10), p<0.05; 10 mo: −0.07 (0.91) vs −0.62 (1.02), p<0.05; 11 mo: −0.05 (0.91) vs −0.69 (1.01), p<0.05; 12 mo: 0.14 (0.90) vs −0.60 (0.91), p=0.001; [underlined: WLZ @ 5 mo - 12 mo (Mean (SD))]; Group x time interaction: p=0.015; 5 mo: 0.18 (0.73) vs 0.16 (0.88), p=NS; 7 mo: 0.40 (0.79) vs 0.55 (0.95), p=NS; 8 mo: 0.57 (0.84) vs 0.68 (0.94), p=NS; 9 mo: 0.51 (0.78) vs 0.82 (0.96), p=NS; 10 mo: 0.53 (0.80) vs 0.84 (0.98), p=NS; 11 mo: 0.63 (0.68) vs 0.88 (0.88), p=0.03; 12 mo: 0.48 (0.75) vs 0.92 (0.88), p=0.03 | [underlined: Model adjustments:] NA (participants matched by sex and race/ethnicity); [underlined: Funding:] NIH (NIDDK); NIH/National Center for Advancing Translational Sciences Colorado Clinical and Translational Science Awards; Abbott Nutrition; American Heart Association; the Beef Checkoff (National Cattlemen's Beef Association); Leprino Foods; National Pork Board.
Tang, 2019 (https://pubmed.ncbi.nlm.nih.gov/30413312/)^46^; RCT-Parallel, U.S.; [underlined: Analytic N by group:] Meat: n=27, Dairy: n=26; [underlined: Attrition:] Meat: 23%; Dairy: 28% (Excluded participants who moved, were not compliant, switched formula, or lost contact); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race/ethnicity:] NR; [underlined: Maternal education:] NR; [underlined: Other SEP measure(s):] NR; [underlined: Maternal age:] ~30 y; [underlined: Milk feeding practices:] 100% exclusively formula-fed infants; [underlined: Child sex (female):] ~53%; [underlined: Birth weight:] ~3.3 kg; [underlined: Gestational age:] ~39 wk | [underlined: Intervention(s):] Meat-based complementary foods (pureed meats) from 5 mo to 12 mo of age in addition to infant formula (same formula given to both groups). (Total protein intake, including formula, ~3g/kg/d.) Fruit and vegetable intake not restricted.; [underlined: Comparator(s):] Dairy-based complementary foods (infant yogurt, cheese, powdered concentrate of 80% whey protein) from 5 mo to 12 mo of age in addition to infant formula (same formula given to both groups). (Total protein intake, including formula, ~3g/kg/d.) Fruit and vegetable intake not restricted.; [underlined: Dietary assessment methods:] Parental report via calendars to record daily consumption, 3-d diet records completed monthly. Return of unused foods, if any.; [underlined: Compliance:] >90% of protein from solid foods was from the assigned protein group (meat or dairy); <5% was from the alternative; [underlined: Age at intervention:] 5–12 mo; [underlined: Intervention duration:] 7 mo; [underlined: Outcome(s):] Weight, Length, WAZ, LAZ, WLZ; [underlined: Outcome assessment methods:] Length and weight measured by blinded, trained research personnel.; [underlined: Age(s) at outcome assessment:] 24 mo | [underlined: Weight (kg) @ 24 mo (Mean (SD))]; Meat vs Dairy: 12.6 (1.0) vs 12.4 (1.5), p=0.38; [underlined: Length (cm) @ 24 mo (Mean (SD))]; Meat vs Dairy: 89.0 (2.3) vs 87.1 (3.3), p=0.02; [underlined: WAZ @ 24 mo (Mean (SD))]; Data NR, p=0.65; [underlined: LAZ @ 24 mo (Mean (SD))]; Meat vs Dairy: 0.19 (0.62) vs −0.37 (0.88), p=0.01; [underlined: WLZ @ 24 mo (Mean (SD))]; Data NR, p=0.40 | [underlined: Model adjustments:] NA (participants matched by sex and race/ethnicity); [underlined: Funding:] NIH (NIDDK); NIH/National Center for Advancing Translational Sciences Colorado Clinical and Translational Science Awards; Abbott Nutrition; American Heart Association; the Beef Checkoff (National Cattlemen's Beef Association); Leprino Foods; National Pork Board
Wall, 2019 (https://pubmed.ncbi.nlm.nih.gov/30831579/)^54^; RCT-Parallel, GUMLi Study, Australia, New Zealand; [underlined: Analytic N by group:] GUMLi: n=67, Cow's Milk: n=67; [underlined: Attrition:] GUMLi: 16%, Cow's Milk: 16% (Excluded participants who were unable to be contacted, discontinued treatment, or had missing outcome data); [underlined: Adequately powered:] Yes; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race/ethnicity:] European: 67%, Other: 17%, Maori: 9%, Asian: 5%, Pacific: 2%; [underlined: Maternal education:] Mother's highest level of education - tertiary: 74%; [underlined: Other SEP measure(s):] Mother worked before birth: 97%; Current employment status of mother: Full-time caregiver: 28%, Full-time paid employment: 25%, Part-time paid employment: 36%; Father's highest level of education - tertiary: 58%; Father currently employed full-time: 90%; Household income: <$50k: 11%, $50k-70k: 13%, $70k-100k: 25%, $100k-150k: 32%, >$150k: 11%; [underlined: Maternal age:] NR; [underlined: Milk feeding practices:] NR; [underlined: Child sex (female):] 47%; [underlined: Birth weight:] ~3.5 kg; [underlined: Birth length:] ~51 cm; [underlined: Birth BMIZ:] ~−0.03; [underlined: Gestational age:] <37 wk: 6%, 37–39 wk: 41%, Full term: 54% | [underlined: Intervention(s):] Growing Up Milk - Lite; (GUMLi): 300 ml/d, a toddler milk energy matched with cow's milk, but lower in protein (1.7 g) and total fat (1.9 g); fortified with iron, vitamin D, prebiotics, and probiotics; [underlined: Comparator(s):] Cow's milk: 300 ml/d, energy matched with GUMLi but higher in protein (3.1 g) and total fat (3.1 g); unfortified; [underlined: Dietary assessment methods:] Monthly questionnaire (telephone or face-to-face interview) completed by parents or guardians; [underlined: Compliance:] Consumed 300 ml of study milk on 80% of days within monitored interval: GUMLi: 96%, Cow's milk: 97%; [underlined: Age at intervention:] 12 mo; [underlined: Intervention duration:] 12 mo; [underlined: Outcome(s):] Weight, WAZ, length, LAZ, BMI, BMIZ, WLZ, WC, WHR, body fat %, fat free mass, fat mass, fat mass index; [underlined: Outcome assessment methods:] Weight and length measured by study personnel. Body composition measured by bioelectrical impedance. Z-scores based on WHO growth standards; [underlined: Age(s) at outcome assessment:] 18, 24 mo | GUMLi vs Cow's milk (ref); [underlined: Weight (kg) @ 18, 24 mo (mean difference (95% CI))]; 18 mo: −0.15 (−0.37, 0.06), p=0.157; 24 mo: −0.19 (−0.4, 0.03), p=0.089; [underlined: WAZ @ 18, 24 mo (mean difference (95% CI))]; 18 mo: −0.13 (−0.27, 0.01), p=0.075; 24 mo: −0.11 (−0.25, 0.03), p=0.124; [underlined: Length (cm) @ 18, 24 mo (mean difference (95% CI))]; 18 mo: −0.69 (−1.25, −0.14), p=0.015; 24 mo: −0.4 (−0.96, 0.17), p=0.165; [underlined: LAZ @ 18, 24 mo (mean difference (95% CI))]; 18 mo: −0.27 (−0.45, −0.08), p=0.005; 24 mo: −0.12 (−0.31, 0.06), p=0.191; [underlined: WLZ @ 18, 24 mo (mean difference (95% CI))]; 18 mo: −0.04 (−0.23, 0.15), p=0.655; 24 mo: −0.12 (−0.31, 0.08), p=0.233; [underlined: BMI @ 18, 24 mo (mean difference (95% CI))]; 18 mo: −0.03 (−0.32, 0.27), p=0.861; 24 mo: −0.14 (−0.44, 0.16), p=0.372; [underlined: BMIZ @ 18, 24 mo (mean difference (95% CI))]; 18 mo: −0.01 (−0.22, 0.2), p=0.932; 24 mo: −0.11 (−0.32, 0.1), p=0.304; [underlined: Body fat (%) @ 18, 24 mo (mean difference (95% CI))]; 18 mo: −0.46 (−2.54, 1.61), p=0.660; 24 mo: −2.19 (−4.24, −0.15), p=0.036; 18 mo (Per-Protocol): −0.61 (−2.7, 1.47), p=0.562; 24 mo (Per-Protocol): −2.09 (−4.16, −0.03), p=0.047; GUMLi vs Cow's milk (ref); [underlined: Fat-free mass (kg) @ 18, 24 mo (mean difference (95% CI))]; 18 mo: −0.14 (−0.45, 0.17), p=0.364; 24 mo: 0.05 (−0.26, 0.36), p=0.749; 18 mo (Per-Protocol): −0.12 (−0.43, 0.19), p=0.448; 24 mo (Per-Protocol): 0.04 (−0.27, 0.35), p=0.799; [underlined: Fat mass (kg) @ 18, 24 mo (mean difference (95% CI))]; 18 mo: −0.13 (−0.41, 0.16), p=0.389; 24 mo: −0.39 (−0.67, −0.1), p=0.008; 18 mo (Per-Protocol): −0.14 (−0.43, 0.15), p=0.357; 24 mo (Per-Protocol): −0.38 (−0.67, −0.09), p=0.010; [underlined: Fat mass index @ 18, 24 mo (mean difference (95% CI))]; 18 mo: −0.15 (−0.55, 0.25), p=0.454; 24 mo: −0.47 (−0.86, −0.08), p=0.020; 18 mo (Per-Protocol): −0.16 (−0.56, 0.24), p=0.422; 24 mo (Per-Protocol): −0.45 (−0.85, −0.06), p=0.026; [underlined: WC (cm) @ 18, 24 mo (mean difference (95% CI))]; 18 mo: −0.24 (−1.09, 0.61), p=0.579; 24 mo: −0.04 (−0.9, 0.82), p=0.935; [underlined: WHR @ 18, 24 mo (mean difference (95% CI))]; 18 mo: −0.0006 (−0.01, 0.01), p=0.918; 24 mo: 0.000 (−0.01, 0.01), p=0.991 | [underlined: Model adjustments:] Baseline outcome, study location, interaction between treatment and time period.; [underlined: Funding:] Danone Pty. Ltd. (Danone Nutricia Research)
NRCT
Friel, 1997 (https://pubmed.ncbi.nlm.nih.gov/9183479/)^49^; NRCT, Canada; [underlined: Analytic N by group:] EM: n=30, BF: n=29, FF: n=30; [underlined: Attrition:] EM: 14%, BF: 17%, FF: 14% (Excluded participants who switched feeding type during the first 3 mo or were lost to follow-up); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race/ethnicity:] NR; [underlined: Maternal education:] ~5 y postprimary school (EM with significantly lower education); [underlined: Other SEP measure(s):] Blishen score (socioeconomic scale): ~32 (EM with significantly lower social class); [underlined: Maternal age:] ~27 y (EM significantly younger); [underlined: Milk feeding practices:] NA; [underlined: Child sex (female):] 42%; [underlined: Birth weight:] 100% between 2,500–4,500 g; [underlined: Gestational age:] 100% 38–42 wk | [underlined: Intervention(s):] Evaporated milk (EM): cow's milk (fat content not prescribed) evaporated to approximately half its original volume, and parents were instructed to prepare it as 1 part EM and 2 parts water, with sucrose or dextrose (2 tsp per 6 oz) added to achieve 68 kcal/100 ml; [underlined: Comparator(s):] Human milk consumption; Infant formula consumption; [underlined: Dietary assessment methods:] 3-d diet record; phone calls every 2 weeks; [underlined: Compliance:] Those who switched feeding type were dropped from the study; [underlined: Age at intervention:] 0–6 mo; [underlined: Intervention duration:] 6 mo; [underlined: Outcome(s):] Weight, length, HC, WAZ, LAZ, WLZ; [underlined: Outcome assessment methods:] Weight, height, and HC measured by study personnel. Z-scores based on WHO/CDC data; [underlined: Age(s) at outcome assessment:] 3 mo, 6 mo | EM vs BF vs FF; [underlined: WLZ @ 3, 6 mo]; EM vs BF vs FF: Data NR, p=NS; [underlined: Weight (g) @ 3, 6 mo (Mean (SD))]; 3 mo: 6,090 (736) vs 6,097 (686) vs 6,061 (642), p=NS; 6 mo: 7,941 (1,166) vs 7,505 (870) vs 7,870; (921), p=NS; [underlined: Weight gain velocity (g/d) from 0–3 and 3–6 mo (Mean (SD))]; 0–3 mo: 28.1 (7.5) vs 28.3 (7.2) vs 27.6 (6.1), p=NS; 3–6 mo: 20.2 (6.8) vs 15.5 (4.0) vs 20.4 (5.8), p<0.05 for EM vs BF; [underlined: WAZ @ 3, 6 mo]; EM vs BF vs FF: Data NR, p=NS; [underlined: Change in WAZ from 3 to 6 mo]; EM vs BF vs FF: 0.01 (0.56) vs −0.49 (0.37) vs; 0.01 (0.53), p<0.05 for EM vs BF; [underlined: Length (cm) @ 3, 6 mo (Mean (SD))]; 3 mo: 61.3 (2.1) vs 61.4 (1.7) vs 61.4 (2.3), p=NS; 6 mo: 67.6 (2.1) vs 67.4 (2.1) vs 67.9 (2.5), p=NS; [underlined: Length gain velocity (cm/d) from 0–3, 3–6 mo (Mean (SD))]; 0–3 mo: 0.12 (0.02) vs 0.12 (0.01) vs 0.12 (0.01), p=NS; 3–6 mo: 0.07 (0.01) vs 0.07 (0.01) vs 0.07 (0.01), p=NS; [underlined: LAZ @ 3, 6 mo]; EM vs BF vs FF: Data NR, p=NS; EM vs BF vs FF; [underlined: LAZ @ 3, 6 mo]; EM vs BF vs FF: Data NR, p=NS; [underlined: HC (cm) @ baseline, 3, 6 mo (Mean (SD))] 3 mo: 40.7 (1.3) vs 40.9 (1.2) vs 41.1 (1.3), p=NS; 6 mo: 43.42 (1.5) vs 43.19 (1.2) vs 43.97 (1.4), p=NS; [underlined: HC growth velocity (cm/d) from 0–3, 3–6 mo (Mean (SD))]; 0–3 mo: 0.06 (0.01) vs 0.07 (0.01) vs 0.06 (0.01), p=NS; 3–6 mo: 0.032 (0.01) vs 0.027 (0.00), 0.031; (0.01), p<0.05 for EM vs BF | [underlined: Key confounders accounted for:] sex (z-scores only); milk feeding practices; gestational age; baseline anthropometry; [underlined: Key confounders NOT accounted for:] SEP; sex (all outcomes except z-scores); race and/or ethnicity; [underlined: Model adjustments:] None; [underlined: Funding:] Health Canada
Friel, 1999 (https://pubmed.ncbi.nlm.nih.gov/10489720/)^48^; NRCT, Canada; [underlined: Analytic N by group:] EM: n=30, BF: n=28; [underlined: Attrition:] EM: 14%, BF: 20% (Excluded participants who switched feeding type during the first 3 mo or were lost to follow-up); Adequately powered: NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race/ethnicity:] NR; [underlined: Maternal education:] NR; [underlined: Other SEP measure(s):] NR; [underlined: Maternal age:] NR; [underlined: Milk feeding practices:] NA; [underlined: Child sex (female):] NR; [underlined: Birth weight:] 100% between 2,500–4,500 g; [underlined: Gestational age:] 100% 38–42 wk | [underlined: Intervention(s):] Evaporated milk (EM): cow's milk (fat content not prescribed) evaporated to approximately half its original volume, and parents were instructed to prepare it as 1 part EM and 2 parts water, with sucrose or dextrose (2 tsp per 6 oz) added to achieve 68 kcal/100 ml; [underlined: Comparator(s):] Human milk consumption; [underlined: Dietary assessment methods:] 3-d diet record; phone calls every 2 weeks; [underlined: Compliance:] Those who switched feeding type were dropped from the study; [underlined: Age at intervention:] 0–6 mo; [underlined: Intervention duration:] 6 mo; [underlined: Outcome(s):] WAZ, LAZ, WLZ, HC; [underlined: Outcome assessment methods:] Weight, height, and HC measured by study personnel. Z-scores based on WHO/CDC data; [underlined: Age(s) at outcome assessment:] 18 mo | EM vs Human milk; [underlined: WAZ @ 18 mo]; 0.53 (1.4) vs −0.16 (0.9), p<0.05; [underlined: LAZ @ 18 mo]; 0.46 (0.72) vs 0.38 (1.06), p=NS; [underlined: WHZ @ 18 mo]; 0.56 (1.41) vs −0.33 (0.98); [underlined: HC (cm) @ 18 mo]; 48 (1.7) vs 49 (6.4), p=NS | [underlined: Key confounders accounted for:] sex (z-scores only); milk feeding practices; gestational age; baseline anthropometry; [underlined: Key confounders NOT accounted for:] sex (HC only); SEP; race and/or ethnicity; [underlined: Model adjustments:] None; [underlined: Funding:] Health Canada
PCS
Farris, 1982 (https://pubmed.ncbi.nlm.nih.gov/7064877/)^14^; PCS, Bogalusa Heart Study, U.S.; [underlined: Analytic N] = 285 (Excluded participants without outcome measurements at 6 mo or 1 y and consuming multiple milk sources); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race/ethnicity:] White: ~59%, Black: ~41%; [underlined: Maternal education:] NR; [underlined: Other SEP measure(s):] NR; [underlined: Maternal age:] NR; [underlined: Milk feeding practices:] BM at 6 mo: 1%, Soy-based formula at 6 mo: 7%, Milk-based formula at 6 mo: 42%; [underlined: Child sex (female):] NR; [underlined: Birth size:] NR; [underlined: Gestational age:] NR | [underlined: Exposure(s) and comparator(s):] Cow's milk vs Milk formula vs Soy formula; [underlined: Dietary assessment methods:] Infant Feeding Practices Questionnaires and dietary questionnaires completed by mothers; [underlined: Age(s) at dietary assessment:] 1, 2, and 4 mo (infant feeding practices questionnaires); 6 mo and 1 y (dietary questionnaires); [underlined: Amounts consumed:] Cow's milk: 49%, Milk formula: 44%, Soy formula: 7%; [underlined: Outcome(s):] Length, weight, skinfold (subscapular); [underlined: Outcome assessment methods:] Weight, length and skinfolds measured by trained personnel; [underlined: Age(s) at outcome assessment:] 6 mo, 1 y | [underlined: Weight (kg) @ 1 y (mean (2 SE))]; Cow's milk vs Milk formula vs Soy formula; 9.8 (0.19) vs 9.8 (0.21) vs 9.4 (0.58), p=NS; [underlined: Length (cm) @ 1 y (mean (2 SE))]; Cow's milk vs Milk formula vs Soy formula; 75.2 (0.53) vs 75.2 (0.45) vs 74.9 (1.29), p=NS; [underlined: Subscapular skinfold (mm) @ 1 y (mean (2 SE))]; Cow's milk vs Milk formula vs Soy formula; 7.8 (3.85) vs 7.4 (0.34) vs 7.0 (0.88), p=NS | [underlined: Key confounders accounted for:] sex; race and/or ethnicity; [underlined: Key confounders NOT accounted for:] SEP; milk feeding practices; gestational age; baseline anthropometry; [underlined: Model adjustments:] None; [underlined: Funding:] National Heart and Lung Institute of the U.S. Public Health Service; Specialized Center of Research-Arteriosclerosis at Louisana State University Medical Center
Garden, 2011 (https://pubmed.ncbi.nlm.nih.gov/21346718/)^30^; PCS, CAPS, Australia; [underlined: Analytic N] = 362 (Excluded participants with missing data on diet or anthropometrics); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race/ethnicity:] Grandparents ethnicity/country of birth: Caucasian: 55%, European: 9%, Middle Eastern: 4%, Indian: 5%, Asian: 4%, Undefined: 24%; [underlined: Maternal education:] NR; [underlined: Other SEP measure(s):] Paternal education: ≤10 y: 33%, 11–12 y: 18%, Tertiary education: 48%; [underlined: Maternal age:] NR; [underlined: Milk feeding practices:] BF ≥6 mo: 42%; [underlined: Child sex (female):] 49%; [underlined: Birth weight:] 3,493 (492) g; [underlined: Gestational age:] NR; [underlined: Other relevant characteristics:] Secondary analysis of RCT (testing intervention of house dust mite avoidance and omega-3 supplementation); all children recruited at increased risk of developing asthma | [underlined: Exposure(s) and comparator(s):] Milk (skim, whole and evaporated), Dairy foods (combined milk and milk products: yogurt, cheese, ice cream, custard) (continuous as quintiles; amounts); [underlined: Dietary assessment methods:] 3-d weighed food records; [underlined: Age(s) at dietary assessment:] 18 mo; [underlined: Amounts consumed:] Quintiles of g or % total energy intake; Milk; g: 0, 157, 356, 491, 643, % energy: 0, 11, 23, 30, 38; Dairy foods; g: 0, 278, 437, 561, 693, % energy: 0, 23, 33, 39, 47; [underlined: Outcome(s):] BMI, waist circumference; [underlined: Outcome assessment methods:] Weight, length, and waist circumference measured by study nurses; [underlined: Age(s) at outcome assessment:] 8 y | [underlined: BMI @ 8 y (Coefficient (95% CI))]; Milk, per quintile; g: −0.11 (−0.32, 0.11), p for trend=0.33; % of total energy: −0.17 (−0.38, 0.03), p for trend=0.10; Dairy foods, per quintile; g: −0.20 (−0.41, 0.02), p for trend=0.07; % of total energy: −0.21 (−0.41, 0.01), p for trend=0.04; [underlined: WC (cm) @ 8 y (Coefficient (95% CI))]; Milk, per quintile; g: −0.30 (−0.87, 0.28), p for trend=0.31; % of total energy: −0.21 (−0.76, 0.34), p for trend=0.45; Dairy foods, per quintile; g: −0.51 (−1.09, 0.07), p for trend=0.08; % of total energy: −0.45 (−0.99, 0.08), p for trend=0.10 | [underlined: Key confounders accounted for:] SEP; sex; race and/or ethnicity; milk feeding practices; gestational age; [underlined: Key confounders NOT accounted for:] baseline anthropometry; [underlined: Model adjustments:] sex, asthma study intervention group, birth weight, breastfeeding for at least 6 months, parental obesity status, ethnicity, smoking in pregnancy and father’s education, total energy intake (food intake in grams only); [underlined: Funding:] The National Health and Medical Research Council of Australia; Cooperative Research Centre for Asthma; New South Wales Department of Health; Children’s Hospital Westmead; University of Sydney, Faculty of Medicine; Commonwealth Department of Health and Aging
Garden, 2012 (https://pubmed.ncbi.nlm.nih.gov/23201761/)^29^; PCS, CAPS, Australia; [underlined: Analytic N] = 298 (Excluded participants who were not still participating in the study at 11.5 y or did not have dietary data.); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race/ethnicity:] NR (Australian born mother: 74%, Australian born father: 69%; Child's grandparents ethnicity/country of birth: Caucasian: ~54%, European: ~9%, Middle Eastern/Indian/Asian: ~12%, Undefined: ~25%); [underlined: Maternal education:] 52% tertiary educated; [underlined: Other SEP measure(s):] Full-time employment: Mother: 49%, Father: 87%; [underlined: Maternal age:] 29.0 (5.1) y; [underlined: Milk feeding practices:] BF duration: 0 to <3 mo: 40%, 3 to <6 mo: 16.8%, ≥6 mo: 43.2%; [underlined: Child sex (female):] 49%; [underlined: Birth weight:] 100% ≥2.5 kg; [underlined: Gestational age:] 100% ≥36 wk; [underlined: Other relevant characteristics:] Secondary analysis of RCT (testing intervention of house dust mite avoidance and omega-3 supplementation); all children recruited at increased risk of developing asthma | [underlined: Exposure(s) and comparator(s):] Milk (skim, whole, and evaporated milk), Dairy foods (combined milk and milk products: yogurt, cheese, ice cream, custard) (continuous; amount); [underlined: Dietary assessment methods:] Parent/caregiver completed 3-d weighed food record (2 weekdays and 1 weekend day); [underlined: Age(s) at dietary assessment:] 18 mo; [underlined: Amounts consumed:] See results for intake data; [underlined: Outcome(s):] BMI trajectory; [underlined: Outcome assessment methods:] Weight and height measured by study nurses. Three BMI trajectories defined using latent basis growth mixture model in relationship to CDC percentiles, stratified by sex.; [underlined: Age(s) at outcome assessment:] 1, 3, 6, 9, 12, 18 mo, 2–5 y (every 6 mo), 8 y, 11.5 y | [underlined: BMI trajectory @ birth-11.5 y (median intake at 18 mo by trajectory group)]; Milk; Boys: normal trajectory: 478.8 g, early and persistent trajectory: 401.1 g, late BMI increase:; 407.0 g, p=0.46; Girls: normal trajectory: 398.7 g, early and persistent trajectory: 510.0 g, late BMI increase:; 380.8 g, p=0.74; Dairy foods; Boys: normal trajectory: 554.3 g, early and persistent trajectory: 433.1 g, late BMI increase:; 527.2 g, p=0.24; Girls: normal trajectory: 473.1 g, early and persistent trajectory: 576.5 g, late BMI increase:; 480.9 g, p=0.45 group); Results analyzed by % of total energy were similar. | [underlined: Key confounders accounted for:] sex; race and/or ethnicity; milk feeding practices; baseline anthropometry (timing of any). SEP; sex; race/ethnicity; milk feeding practices; baseline anthropometry (types and amounts, multinomial regression only).; [underlined: Key confounders NOT accounted for:] SEP; gestational age (timing of any). gestational age (types and amounts).; [underlined: Model adjustments:] None (timing of any); dietary intervention group, BF, parental obesity, ethnicity, smoking during pregnancy, father's education status (types and amounts, multinomial regression only); [underlined: Funding:] National Health and Medical Research Council of Australia
Goh, 2022 (https://pubmed.ncbi.nlm.nih.gov/35267902/)^50^; PCS, NHID, Korea; [underlined: Analytic N] = 142,668 (Excluded participants with missing data on body weight or height, errors on age of measurement, and extreme outliers (BMI ≤4 or ≥50)); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race/ethnicity:] NR; [underlined: Maternal education:] NR; [underlined: Other SEP measure(s):] Household income (units NR): 11.81 (4.44); [underlined: Maternal age:] NR; [underlined: Milk feeding practices:] Type of milk feeding at 4–6 mo: BM: 46.32%, Formula: 32.94%, Mixed milk: 20.35%, Special formula milk: 0.40%; [underlined: Child sex (female):] 49%; [underlined: Birth weight:] 3.20 (0.46) kg; [underlined: Gestational age:] Preterm birth: 3.67% | [underlined: Exposure(s) and comparator(s):] Goat’s milk, soy milk, cow's milk, BM (ref); [underlined: Dietary assessment methods:] Parental questionnaire; [underlined: Age(s) at dietary assessment:] 12 mo; [underlined: Amounts consumed:] BM: Boys: 38.81%, Girls: 40.77%; Goat’s milk: Boys: 2.99%, Girls: 2.83%; Soy milk: Boys: 4.05%, Girls: 3..86%; Cow's milk: Boys: 4.25%, Girls: 4.43%; Formula milk: Boys: 49.88%, Girls: 48.10%; [underlined: Outcome(s):] Early adiposity rebound; [underlined: Outcome assessment methods:] Height and weight measured by trained medical staff. Early adiposity rebound defined as rebound of BMI percentile before 4 y. BMI percentile by age and sex was based on WHO Child Growth Standards.; [underlined: Age(s) at outcome assessment:] 4–6 mo, 9–12 mo, 18–24 mo, 30–36 mo, 42–48 mo, 54–60 mo, 66–71 mo | [underlined: Early adiposity rebound (<4 y) (OR)]; Cow’s milk vs BM (ref) Boys: 1.51, p=0.009; Girls: 1.51, p=0.009; Goat’s Milk vs BM (ref) Boys: Data NR, p=NS Girls: Data NR, p=NS; Soy Milk vs BM (ref) Boys: 1.47, p=0.021; Girls: 1.46, p=0.016 | [underlined: Key confounders accounted for:] SEP; sex; milk feeding practices; baseline anthropometry; [underlined: Key confounders NOT accounted for:] race and/or ethnicity; gestational age; [underlined: Model adjustments:] Birth weight, preterm birth, household income; type of feeding milk (4–6 mo); number of weaning food per day, type of feeding milk (9–12 mo); use of salt in food, vitamin supplements (18–24 mo); appetite, number of meals per day, number of snacks per day, daily intake of cow's milk, daily intake of SSB, parents' concern about child's eating habits (30–36 mo); number of meals per day, daily intake of cow's milk, daily intake of SSB (42–48 mo); [underlined: Funding:] Dong-A University
Hopkins, 2015 (https://pubmed.ncbi.nlm.nih.gov/26354544/)^51^; PCS, Child in Focus substudy of ALSPAC, U.K.; [underlined: Analytic N] = 1,112 (n by analysis varied from 641–948) (Excluded participants born <37 wk gestation and with missing dietary information at 8 mo); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race/ethnicity:] NR; [underlined: Maternal education:] Low: 22.5%, Medium: 35.2%, High: 42.3%; [underlined: Other SEP measure(s):] NR; [underlined: Maternal age:] NR; [underlined: Milk feeding practices:] BM at 8 mo: BM group: 396 ml/d, Cow's milk groups (high and low): 0 ml/d; [underlined: Child sex (female):] 46%; [underlined: Birth weight:] 3.5 (0.47) kg; [underlined: Birth length:] 50.9 (1.97) cm; [underlined: Birth BMI:] 13.5 (1.20); [underlined: Gestational age:] 100% ≥37 wk | [underlined: Exposure(s) and comparator(s):] Cow's milk (high or low) vs BM (ref) at 8 mo; [underlined: Dietary assessment methods:] 3-d unweighed food records completed by child's main carer; [underlined: Age(s) at dietary assessment:] 8 mo; [underlined: Amounts consumed:] Cow's milk intake (mean (95% CI)) at 8 mo: High cow's milk group (≥600 ml/d): 765 (733, 798) ml/d, Low cow's milk group (<600 ml/d): 441 (413, 469) ml/d, BM group: 70 (55, 84) ml/d; [underlined: Outcome(s):] Weight, height, BMI; [underlined: Outcome assessment methods:] Weight and height measured by trained staff. Sex and age specific SDS calculated based on UK 1990 growth reference.; [underlined: Age(s) at outcome assessment:] 12, 18, 25, 31, 37, 43, 49, 61 mo; 7, 9, 10 y | [underlined: Weight (SDS) @ 12, 18, 25, 31, 37, 43, 49, 61 mo; 7 y, 9 y, 10 y (mean difference (95% CI))]; Low cow's milk vs BM (ref); 12 mo: 0.30 (0.02, 0.59), p<0.05; 18 mo: 0.33 (0.03, 0.63), p<0.05; 25 mo: 0.29 (−0.01, 0.58); 31 mo: 0.27 (−0.02, 0.57); 37 mo: 0.21 (−0.08, 0.51); 43 mo: 0.16 (−0.15, 0.47); 49 mo: 0.09 (−0.21, 0.39); 61 mo: 0.14 (−0.19, 0.47); 7 y: −0.00 (−0.32, 0.32); 9 y: −0.02 (−0.33, 0.29); 10 y: 0.18 (−0.13, 0.49); High cow's milk vs BM (ref); 12 mo: 0.64 (0.35, 0.94), p<0.001; 18 mo: 0.62 (0.31, 0.93), p<0.001; 25 mo: 0.52 (0.22, 0.81), p<0.001; 31 mo: 0.55 (0.25, 0.85), p<0.001; 37 mo: 0.46 (0.16, 0.77), p<0.01; 43 mo: 0.38 (0.06, 0.70), p<0.05; 49 mo: 0.46 (0.16, 0.77), p<0.01; 61 mo: 0.43 (0.10, 0.76), p<0.05; 7 y: 0.13 (−0.20, 0.47); 9 y: 0.45 (0.14, 0.77), p<0.01; 10 y: 0.46 (0.13, 0.78), p<0.01; [underlined: Height (SDS) @ 12, 18, 25, 31, 37, 43, 49, 61 mo; 7 y, 9 y, 10 y (mean difference (95% CI))]; Low cow’s milk vs BM (ref): 12 mo: 0.13 (−0.14, 0.40); 18 mo: 0.22 (−0.06, 0.50); 25 mo: 0.20 (−0.08, 0.47); 31 mo: 0.17 (−0.10, 0.45); 37 mo: 0.16 (−0.12, 0.43); 43 mo: 0.06 (−0.23, 0.35); 49 mo: 0.02 (−0.26, 0.30); 61 mo: −0.00 (−0.30, 0.29); 7 y: −0.15 (−0.43, 0.14); 9 y: −0.17 (−0.46, 0.11); 10 y: −0.07 (−0.36, 0.22); High cow’s milk vs BM (ref); 12 mo: 0.46 (0.18, 0.74), p<0.01; 18 mo: 0.58 (0.29, 0.86), p<0.001; 25 mo: 0.47 (0.18, 0.75), p<0.01; 31 mo: 0.42 (0.14, 0.71), p<0.01; 37 mo: 0.44 (0.15, 0.73), p<0.01; 43 mo: 0.38 (0.09, 0.68), p<0.05; 49 mo: 0.31 (0.02, 0.60), p<0.05; 61 mo: 0.21 (−0.09, 0.51); 7 y: 0.05 (−0.25, 0.35); 9 y: 0.12 (−0.17, 0.42); 10 y: 0.30 (0.00, 0.59), p<0.05; [underlined: BMI (SDS) @ 12, 18, 25, 31, 37, 43, 49, 61 mo; 7 y, 9 y, 10 y (mean difference (95% CI))]; Low cow’s milk vs BM (ref):; 12 mo: 0.29 (0.01, 0.58), p<0.05; 18 mo: 0.25 (−0.06, 0.56); 25 mo: 0.23 (−0.07, 0.53); 31 mo: 0.23 (−0.07, 0.52); 37 mo: 0.17 (−0.13, 0.46); 43 mo: 0.16 (−0.17, 0.48); 49 mo: 0.10 (−0.20, 0.40); 61 mo: 0.20 (−0.14, 0.55); 7 y: 0.13 (−0.20, 0.46); 9 y: 0.07 (−0.24, 0.38); 10 y: 0.32 (−0.01, 0.64); High cow’s milk vs BM (ref); 12 mo: 0.46 (0.17, 0.75), p<0.01; 18 mo: 0.35 (0.03, 0.66), p<0.05; 25 mo: 0.25 (−0.05, 0.55); 31 mo: 0.35 (0.05, 0.65), p<0.05; 37 mo: 0.25 (−0.06, 0.56); 43 mo: 0.20 (−0.14, 0.53); 49 mo: 0.38 (0.08, 0.69), p<0.05; 61 mo: 0.45 (0.10, 0.79), p<0.05; 7 y: 0.15 (−0.19, 0.50); 9 y: 0.54 (0.22, 0.86), p<0.01; 10 y: 0.44 (0.10, 0.78), p<0.05 | [underlined: Key confounders accounted for:] SEP; sex; gestational age; [underlined: Key confounders NOT accounted for:] race and/or ethnicity; milk feeding practices; baseline anthropometry; [underlined: Model adjustments:] All time points: maternal education, smoking in pregnancy, parity; At 18 mo, 43 mo, 61 mo, 7 y, 10 y: current dietary energy and protein intakes at each age (based on data availability); [underlined: Funding:] United Kingdom Medical Research Council; Wellcome Trust; University of Bristol; Wyeth Nutrition
Smith-Brown, 2018 (https://pubmed.ncbi.nlm.nih.gov/29493037/)^45^; PCS, Feeding Queensland Babies Study Cohort, Australia; [underlined: Analytic N] = 25 (Reasons for exclusion NR); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race/ethnicity:] NR; [underlined: Maternal education:] NR; [underlined: Other SEP measure(s):] NR; [underlined: Maternal age:] NR; [underlined: Milk feeding practices:] NR; [underlined: Child sex (female):] 44%; [underlined: Birth size:] NR; [underlined: Gestational age:] NR | [underlined: Exposure(s) and comparator(s):] Dairy: cow’s milk, yoghurt, cheese, ice cream, dessert, etc (continuous; daily feedings); [underlined: Dietary assessment methods:] 18-item FFQ; [underlined: Age(s) at dietary assessment:] 12 mo; [underlined: Amounts consumed:] 2.57 (1.57) daily feedings (Range: 0.00–6.00); [underlined: Outcome(s):] FMI, FFMI, WHR, BMIZ; [underlined: Outcome assessment methods:] Weight, height, and WC were measured by study personnel. Fat mass and fat free mass were measured using total body water (deuterium oxide dilution technique) converted to age- and sex-specific hydration constants. FMI and FFMI calculated by dividing fat-free/fat mass by square of height. BMIZ calculated using WHO reference data. WHR, FFMI, and FMI z-scores calculated using values calculated from NHANES.; [underlined: Age(s) at outcome assessment:] 2–3 y (Mean: 2.65 y) | [underlined: BMIZ @ 2–3 y (Pearson's correlation)]; r=0.29, p=0.245; [underlined: FMI Z-score @ 2–3 y (Pearson's correlation)]; r=−0.24, p=0.245; [underlined: FFMI Z-score @ 2–3 y (Pearson's correlation)] r=0.51, p=0.040; [underlined: WHR Z-score @ 2–3 y (Pearson's correlation)]; r=0.26, p=0.245 | [underlined: Key confounders accounted for:] None; [underlined: Key confounders NOT accounted for]: SEP; sex; race and/or ethnicity; milk feeding practices; gestational age; baseline anthropometry; [underlined: Model adjustments:] None; [underlined: Funding:] Australian government, Danone Nutricia
Thorisdottir, 2013 (https://pubmed.ncbi.nlm.nih.gov/23988865/)^53^; PCS, Iceland; [underlined: Analytic N] = 234 (Excluded participants with incomplete dietary registration at 9 or 12 mo, anthropometry measurements in infants, or measurements of weight or height at 6 y.); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race/ethnicity:] NR; [underlined: Maternal education:] ≥12 y: ~78%; [underlined: Other SEP measure(s):] NR; [underlined: Maternal age:] ~31 y; [underlined: Milk feeding practices:] BF duration: ~8 mo; EBF duration: ~4 mo; Any formula at 9 mo: ~11%, 12 mo: ~4%; [underlined: Child sex (female):] ~53%; [underlined: Birth weight:] ~3.7 kg; [underlined: Gestational age:] 100% 37–41 wk; [underlined: Other relevant characteristics:] Includes 2 cohorts (before and after changes to infant dietary guidelines regarding cow's milk/dairy in first y) | [underlined: Exposure(s) and comparator(s):] Cow’s milk (continuous, per 100 g); [underlined: Dietary assessment methods:] Weighed food and fluids for 2 or 3 consecutive d; [underlined: Age(s) at dietary assessment:] 9, 12 mo; [underlined: Amounts consumed:] Cow's milk: 9 mo: ~79 g/d, 12 mo: ~107 g/d; [underlined: Outcome(s):] BMI; [underlined: Outcome assessment methods:] Weight and height measured by research personnel.; [underlined: Age(s) at outcome assessment:] 6 y | [underlined: BMI @ 6 y (β (95% CI))]; @ 9 mo: 0.1 (−0.1, 0.2), p=0.28; @ 12 mo: 0.2 (0.0, 0.3), p=0.017 | [underlined: Key confounders accounted for:] SEP; sex; milk feeding practices; gestational age; [underlined: Key confounders NOT accounted for:] race and/or ethnicity; baseline anthropometry; [underlined: Model adjustments:] Cohort, sex, energy intake at 9 or 12 mo, birth weight, duration of BF, mother's education; [underlined: Funding:] NR
Wosje, 2001 (https://pubmed.ncbi.nlm.nih.gov/11209585/)^55^; PCS, U.S.; [underlined: Analytic N] = 51 (Excluded participants lost to follow-up during the original trial, without completed 3-d diet records at 12, 18, and 24 mo, and those who consumed both 2% and whole milk after 12 mo.); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race/ethnicity:] White: 94%, Other: 6%; [underlined: Maternal education:] ~14 y; [underlined: Other SEP measure(s):] NR; [underlined: Maternal age:] NR; [underlined: Milk feeding practices:] NR; [underlined: Child sex (female):] 45%; [underlined: Birth weight:] None with SGA; [underlined: Gestational age:] 100% term (37–42 wk); [underlined: Other relevant characteristics:] Secondary analysis of RCT assessing effect of timing of introduction of solid foods (3 mo vs 6 mo) on growth and body composition. | [underlined: Exposure(s) and comparator(s):] Only 2% milk vs Only whole milk; [underlined: Dietary assessment methods:] 3-d diet record completed by parents; [underlined: Age(s) at dietary assessment:] 12, 18, and 24 mo; [underlined: Amounts consumed:] 2% milk: 55%, whole milk: 45% (Intake at 24 mo: 2% milk: 351 (186) g, whole milk: 531 (360) g); [underlined: Outcome(s):] Weight, WAZ, weight gain, WAZ change, length, LAZ, length gain, LAZ change, % body fat, % body fat change, fat mass gain; [underlined: Outcome assessment methods:] Weight and length measured by study personnel. Body fat measured by DXA. Z scores calculated using National Center for Health Statistics (NCHS) growth charts.; [underlined: Age(s) at outcome assessment:] 12, 18 (weight, length only), and 24 mo | 2% vs whole milk; [underlined: Length (cm) @ 18, 24 mo (Mean (SD))]; 18 mo: 81.9 (4.8) vs 82.8 (3.2), p=NS; 24 mo: 87.9 (3.4) vs 87.8 (3.2), p=NS; [underlined: LAZ @ 24 mo (Mean (SD))]; 24 mo: 0.14 (0.58) vs 0.15 (0.59), p=NS; [underlined: Length gain (cm) from 12–24 mo (Mean (SD))]; 12.4 (2.2) vs 11.7 (1.7), p=NS; [underlined: LAZ change from 12–24 mo (Mean (SD))]; −0.10 (0.42) vs −0.04 (0.28), p=NS; [underlined: Weight (kg) @ 18, 24 mo (Mean (SD))]; 18 mo: 11.4 (1.3) vs 11.6 (3.0), p=NS; 24 mo: 12.8 (1.5) vs 12.7 (1.3), p=NS; [underlined: WAZ @ 24 mo (Mean (SD))]; 24 mo: 0.23 (0.64) vs 0.20 (0.62), p=NS; [underlined: Weight gain (kg) from 12–24 mo (Mean (SD))]; 3.0 (0.7) vs 2.7 (0.7); [underlined: WAZ change from 12–24 mo (Mean (SD))]; 0.27 (0.35) vs 0.10 (0.31), p=NS; [underlined: % body fat @ 24 mo (Mean (SD))]; 24 mo: 26.5% (5.5%) vs 27.4% (5.7%), p=NS; [underlined: % body fat change from 12–24 mo (Mean (SD))]; −2.8 (4.2) vs −2.5 (5.0), p=NS; [underlined: Fat mass gain (g) from 12–24 mo (Mean (SD)]); 492 (559) vs 452 (838), p=NS | [underlined: Key confounders accounted for:] SEP; sex; gestational age; baseline anthropometry; [underlined: Key confounders NOT accounted for:] race and/or ethnicity; milk feeding practices; [underlined: Model adjustments:] None; [underlined: Funding:] Gerber Products, NIH

a Abbreviations: @: at; ALSPAC: Avon Longitudinal Study of Parents and Children; BF: breast feeding; BM: breast milk; BMI: body mass index; BMIZ: body mass index z-score; CAPS: Childhood Asthma Prevention Study; CI: confidence interval; cm: centimeter; d: day; DXA: dual-energy X-ray absorptiometry; EBF: exclusive breast feeding; EM: evaporated milk; etc: et cetera; FFMI: fat-free mass index; FMI: fat mass index; g: gram; GUMLi: Growing-Up Milk-Lite; HC: head circumference; kg: kilogram; LAZ: length-for-age z-score; ml: milliliter; mo: month; NA: not applicable; NHID: National Health Information Database; NR: not reported; NRCT: non-randomized controlled trial; NS: non-significant; OR: odds ratio; oz: ounce; PCS: prospective cohort study; RCT: randomized controlled trial; ref: reference; SD: standard deviation; SDS: standard deviation score; SEP: socioeconomic position; SGA: small-for-gestational age; SSB: sugar-sweetened beverage; tsp: teaspoon; U.K.: United Kingdom; U.S.: United States; WAZ: weight-for-age z-score; WC: waist circumference; WHR: waist-to-height ratio; WHZ: weight-for-height z-score; wk: week; WLZ: weight-for-length z-score; y: year

Table 50 Risk of bias for randomized controlled trials (parallel) examining dairy consumption and growth, body composition, and risk of obesity ^a^

Article | Randomization | Deviations from intended interventions (effect of assignment or per-protocol) | Missing outcome data | Outcome measurement | Selection of the reported result | Overall risk of bias
Larnkjaer, 2009^52^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Tang, 2018^47^ | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS
Tang, 2019^33^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Wall, 2019^54^ | LOW | LOW | LOW | LOW | LOW | LOW

a Possible ratings of low, some concerns, or high determined using the "Cochrane Risk-of-bias 2.0" (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2019 version)” ( Sterne JAC, Savović J, Page MJ, Elbers RG, Blencowe NS, Boutron I, Cates CJ, Cheng H-Y, Corbett MS, Eldridge SM, Hernán MA, Hopewell S, Hróbjartsson A, Junqueira DR, Jüni P, Kirkham JJ, Lasserson T, Li T, McAleenan A, Reeves BC, Shepperd S, Shrier I, Stewart LA, Tilling K, White IR, Whiting PF, Higgins JPT. RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ 2019; 366: l4898.31462531

Table 51 Risk of bias for non-randomized controlled trials examining dairy consumption and growth, body composition, and risk of obesity ^b^

Article | Confounding | Selection of participants | Classification of interventions | Deviations from intended interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Friel, 1997^49^ | CRITICAL | LOW | LOW | LOW | MODERATE | LOW | MODERATE | CRITICAL
Friel, 1999^48^ | CRITICAL | LOW | LOW | LOW | MODERATE | LOW | MODERATE | CRITICAL

b Possible ratings of low, moderate, serious, critical, or no information determined using the “Risk of Bias in Non-randomized Studies of Interventions (ROBINS-I) tool (https://www.riskofbias.info/welcome/home/current-version-of-robins-i)” ( Sterne JAC, Hernán MA, Reeves BC, Savović J, Berkman ND, Viswanathan M, Henry D, Altman DG, Ansari MT, Boutron I, Carpenter JR, Chan AW, Churchill R, Deeks JJ, Hróbjartsson A, Kirkham J, Jüni P, Loke YK, Pigott TD, Ramsay CR, Regidor D, Rothstein HR, Sandhu L, Santaguida PL, Schünemann HJ, Shea B, Shrier I, Tugwell P, Turner L, Valentine JC, Waddington H, Waters E, Wells GA, Whiting PF, Higgins JPT. ROBINS-I: a tool for assessing risk of bias in non-randomized studies of interventions. BMJ 2016; 355; i4919; doi: 10.1136/bmj.i4919.)27733354

Table 52 Risk of bias for observational studies examining dairy consumption and growth, body composition, and risk of obesity ^a^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Garden, 2011^30^ | SOME CONCERNS | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Garden, 2012^29^ | SOME CONCERNS | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Goh, 2022^50^ | SOME CONCERNS | HIGH | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Hopkins, 2015^51^ | HIGH | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Smith-Brown, 2018^45^ | VERY HIGH | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | VERY HIGH
Thorisdottir, 2013^53^ | SOME CONCERNS | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Wosje, 2001^55^ | VERY HIGH | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | VERY HIGH

a Possible ratings of low, some concerns, high, very high, no information, or not applicable determined using the "Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)" tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602. ) *Low risk of bias except for concerns about uncontrolled confounding.

### Sugar-sweetened beverages

Twelve PCS (17 articles) met inclusion criteria and examined the relationship between the consumption of SSBs by infants and young children, up to age 24 months, and growth, body composition, and risk of obesity.^1,23,27–30,50,56–65^ This data was synthesized as part of the systematic review with meta-analysis on SSB intake and growth, body composition, and risk of obesity across the lifespan; to avoid duplication of effort, details of the review of this evidence are presented in that report. Briefly, the Committee developed a conclusion statement about the relationship between SSB consumption and growth, body composition, and risk of obesity based on their review of the totality of evidence in infants, children, and adolescents (Table 53).

Table 53 Conclusion statement, grade for sugar-sweetened beverage consumption and growth, body composition, and risk of obesity in infants, children, and adolescents^*^ * Excerpted from: Deierlein AL, Raynor HA, Byrd-Bredbenner C, . Sugar-Sweetened Beverages and Growth, Body Composition, and Risk of Obesity: A Systematic Review with Meta-Analysis. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review; 2024. 10.52570/NESR.DGAC2025.SR05

Conclusion Statement | Sugar-sweetened beverage consumption by infants, children, and adolescents is associated with unfavorable growth patterns and body composition, and higher risk of obesity in childhood up to early adulthood. This conclusion statement is based on evidence graded as moderate.
Grade | Moderate
Body of Evidence | 5 RCTs (all in meta-analysis); 107 observational studies (72 in meta-analyses)
Consistency | Consistent directionality of findings across articles; some heterogeneity
Precision | Few concerns with precision
Risk of bias | Some concerns with risk of bias, primarily due to confounding and missing data in observational studies
Directness | Few concerns with directness across studies
Generalizability | Some concerns with generalizability to the U.S. population, particularly in the RCT data, and limited data included in meta-analyses for infants/young children

### Food sources of added sugars

#### Description of the evidence

Four studies (from 5 articles) met inclusion criteria and examined the relationship between consumption of food sources of added sugars among infants and young children, up to age 24 months, and growth, body composition, and risk of obesity (Table 55).^1,27,29,30,40^ All studies were PCS,^1,27,29,30,40^ using data from the following cohorts: Born in Bradford 1000,^27^ CAPS,^29,30^ Nurture,^40^ and 1 unnamed study.1 One study was a secondary analysis of a RCT testing the impact of house dust mite avoidance and omega-3 supplementation on allergy prevention.^29,30^

##### Population

Two studies were conducted in the United States,^1,40^ and 1 study each was conducted in Australia,^29,30^ and the United Kingdom.^27^ The analytic sample sizes of the studies ranged from 68^1^ to 779.^27^ None of the studies reported power calculations related to consumption of food sources of added sugars and the relevant outcomes.

All studies provided information on the racial and/or ethnic background of participants, and this varied across the studies. In 1 study 100% or participants were Hispanic,^1^ approximately 56% and 44% of participants were Pakistani and White British, respectively, in another,^27^ 71.5% of participants were Black, with the remaining participants being White (19.2%), Latina (6.5%), or of other race and/or ethnicity (8.9%) in the third,^40^ and the participants’ grandparents’ ethnicity or country of birth was Caucasian (55%), European (9%), Indian (5%), 4% Middle Eastern (4%), Asian (4%), or undefined (24%) in the final study.^29,30^ Across the 3 studies that reported maternal age, the mean age of the women tended to be in the late twenties.^1,29,40^ Human milk and formula feeding practices were reported in 3 studies and tended to vary: 1 study reported that 51% exclusively breastfed for at least 1 month, 70.1% ever formula-fed, and 20.8% fed any breastmilk at 10 months,^1^ a second study reported that 40% of the sample had a breastfeeding duration of less than 3 months, 16.8% for 3 up to 6 months, and 43.2% for 6 months or longer,^29^ and the third reported a mean breastfeeding duration of 14.7 weeks.^40^ SEP, including maternal education, was reported for 3 studies.^1,29,30,40^ Mothers tended to have greater than a high school education level.^1,29,30,40^ Across the 3 studies that reported other measures of SEP, 1 exclusively enrolled individuals who participated in WIC,^1^ a second study reported that approximately half of the fathers had a tertiary education,^30^ and a third reported that 55.4% of the sample had a household income of $20,000 or less.^40^

Regarding the characteristics of the infants and young children, the studies, when reported, noted that approximately 50% of participants were female,^1,29,30,40^ mean birth weight was approximately 3.3 kilograms,^27,30^ or mean birth weight for gestational age z-score was −0.31,^40^ and gestational age was greater than ^36^ weeks.^29,40^ One study reported mean baseline (age 18 months) weights and lengths of 11.6 kilograms and 83.4 centimeters, respectively,30 while mean baseline (age 3 months) WLZ was 0.14 in a second study.^40^

##### Exposures and comparators

The food sources of added sugars examined varied slightly across studies. One study examined sweets, defined as cookies, cakes, and candy,^40^; a second examined sweet snacks, which included cakes, biscuits, chocolate, and sweets,^27^ and a third study examined confectionery, which was defined as chocolate, jellies, and energy bars.^29,30^ One study did not provide examples of the types of foods included in the measure of sweets.^1^ The exposures were analyzed continuously,^1,29,30^ and categorically.^27,40^ The studies used a variety of assessment methods to measure consumption of food sources of added sugars, including FFQs,^1,27^ an infant feeding questionnaire,^40^ or 3-day weighed food records.^29,30^ Most of the studies assessed consumption of food sources of added sugars multiple times from birth up to age 24 months.^1,27,40^ Three studies assessed the exposure up to 12 months,^1,27,40^ and 3 studies assessed the exposure between ages 12 and 24 months.^1,27,29,30^

##### Outcomes

Each study assessed a unique measure of growth,^27,29,30,40^ body composition,^30^ and risk of obesity.^1^ including BMI trajectory,^29^ BMI,^30^ BMIZ,^27^ WLZ,^40^ waist circumference,^30^ and risk of elevated WLZ.^1^ Three studies used WHO growth standards^1,27,40^ and 1 study used CDC growth charts^29^ to calculate z-scores. The age of outcome assessment varied widely, ranging from age 6 months up to age 11.5 years. In all studies the outcomes were measured by research staff or nurses.

#### Synthesis of the evidence

The 4 studies that examined food sources of added sugars reported null or mixed findings related to growth, body composition, and risk of obesity (Table 55).^1,27,29,30,40^ Three of the 4 studies reported null associations between confectionery,^29,30^ sweet snacks,^27^ and sweets^1^ on growth, body composition and risk of overweight. The direction of findings of these studies were mixed, with 2 studies reporting non-significant, negative associations between confectionery^30^ or cakes, biscuits, chocolate, and sweets^27^ and growth or body composition, and 1 study reporting a non-significant, positive association between sweets and WLZ.^40^ One study reported mixed findings, with infants “often” consuming sweets, compared to never, had significantly lower or higher WLZ that varied by the age at outcome, while comparisons between infants “sometimes” and never consuming sweets were null.^40^

Overall, the foods examined were consistent. However, the timing of the exposure assessment and outcome indicators varied across studies and were difficult to compare among the few studies that were included in this portion of the systematic review.

#### Conclusion statement and grade

The Committee did not draw a conclusion statement about the relationship between consumption of food sources of added sugars by infants and young children, up to age 24 months, and growth, body composition, and risk of obesity because there is not enough evidence (Table 54). Publication bias may be a limitation, but the small body of evidence makes it difficult to assess. Additionally, while the literature search was comprehensive, a search of the gray literature was not done, which could increase the possibility of publication bias. The risk of bias assessments for the studies that addressed this question are documented in Table 56.

Table 54 Conclusion statement, grade for consumption of foods with added sugars by infants and young children and growth, body composition, and risk of obesity

Conclusion Statement | A conclusion statement cannot be drawn about the relationship between consumption of food sources of added sugars by infants and young children, up to age 24 months, and outcomes related to growth patterns, body composition, and risk of obesity during childhood because there is not enough evidence available.
Grade | Grade Not Assignable
Body of Evidence | 5 articles (4 studies): 4 prospective cohort studies
Rationale | There was not enough evidence available to answer this question.

Table 55 Evidence examining the relationship between consumption of food sources of added sugar and growth, body composition, and risk of obesity ^a^

Study and Participant Characteristics | Intervention/Exposure, Comparator, and Outcome | Results | Key Confounders, Model Adjustments, Funding
Amaro-Rivera, 2019 (https://pubmed.ncbi.nlm.nih.gov/31260549/)^1^; PCS, U.S. (Puerto Rico); [underlined: Analytic N] = 68 (Excluded participants lost to follow-up); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race and/or ethnicity:] Hispanic: 100%; [underlined: Maternal education:] ≤HS: 32.5%, >HS: 67.5%; [underlined: Other SEP measure(s):] WIC participation: 100%; [underlined: Maternal age:] Parent’s age: <30 y: 55.8%, ≥30 y: 44.2%; [underlined: Milk feeding practices:] EBF for ≥1 mo: 51%, Ever FF: 70.1%, Any BF at ~10 mo: 20.8%; [underlined: Child sex (female):] 47%; [underlined: Birth size:] NR; [underlined: Gestational age:] NR | [underlined: Exposure(s) and comparator(s):] Annual change (amounts) in sweets Diet Quality Index Scores (continuous); [underlined: Dietary assessment methods:] Interviewer-administered questionnaire completed by caregivers. Diet Quality Index Score based on semi-quantitative FFQ.; [underlined: Age(s) at dietary assessment:] 0–5, 8–36 mo (types/amounts); [underlined: Amounts consumed:] NR; [underlined: Outcome(s):] WLZ (≥1); [underlined: Outcome assessment methods:] Weight and length measured by trained research staff. Weight status assessed using WHO age- and sex-specific WLZ growth charts. Relative risk for WLZ (≥1 z-score vs <1 z-score), with underweight defined as WLZ ≤- 2 SD, healthy weight status defined as WLZ >-2 and <1 SD, risk of overweight defined as WLZ between 1-<2, and overweight or obesity defined as WLZ ≥2 SD.; [underlined: Age(s) at outcome assessment:] 11–36 mo (Median: 21 mo, 11–23 mo: 61.0%, 24–36 mo: 39.0%) | [underlined: WLZ (≥1 vs <1) @ 11–36 mo (RR (95% CI))]; Sweets score: 1.03 (0.83, 1.27) | [underlined: Key confounders accounted for:] SEP; sex; race and/or ethnicity; milk feeding practices; baseline anthropometry; [underlined: Key confounders NOT accounted for:] gestational age; [underlined: Model adjustments:] WLZ at baseline; [underlined: Funding:] University of Puerto Rico Central Administration Grant; Capacity Advancement in Research Infrastructure; National Institute on Minority Health and Health Disparities
Garden, 2011 (https://pubmed.ncbi.nlm.nih.gov/21346718/)^30^; PCS, CAPS, Australia; [underlined: Analytic N] = 362 (Excluded participants with missing data on diet or anthropometrics); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race and/or ethnicity:] Grandparents ethnicity/country of birth: Caucasian: 55%, European: 9%, Middle Eastern: 4%, Indian: 5%, Asian: 4%, Undefined: 24%; [underlined: Maternal education:] NR; Other SEP measure(s): Paternal education: ≤10 y: 33%, 11–12 y: 18%, Tertiary education: 48%; [underlined: Maternal age:] NR; [underlined: Milk feeding practices:] BF ≥6 mo: 42%; [underlined: Child sex (female):] 49%; [underlined: Birth weight:] 3,493 (492) g; [underlined: Gestational age:] NR; [underlined: Other relevant characteristics:] Secondary analysis of RCT (testing intervention of house dust mite avoidance and omega-3 supplementation); all children recruited at increased risk of developing asthma | [underlined: Exposure(s) and comparator(s):] Confectionary (chocolate, jellies, energy bars): Continuous (amounts; as quartiles); [underlined: Dietary assessment methods:] 3-d weighed food records; [underlined: Age(s) at dietary assessment:] 18 mo; [underlined: Amounts consumed:] Quartiles: g: 0, 1, 7, 15; % total energy intake: 0, 0.3, 3, 6; [underlined: Outcome(s):] BMI, WC; [underlined: Outcome assessment methods:] Weight, length, and waist circumference measured by study nurses; [underlined: Age(s) at outcome assessment:] 8 y | [underlined: BMI @ 8 y (β (95% CI))]; Per quartile; g: −0.25 (−0.49, 0.00), p for trend=0.05; % of total energy: −0.24 (−0.48, 0.01), p for trend=0.06; [underlined: WC (cm) @ 8 y (β (95% CI))]; Per quartile; g: −0.36 (−1.02, 0.30), p for trend=0.28; % of total energy: −0.22 (−0.87, 0.44), p for trend=0.52 | [underlined: Key confounders accounted for:] SEP; sex; race and/or ethnicity; milk feeding practices; gestational age; [underlined: Key confounders NOT accounted for:] baseline anthropometry; [underlined: Model adjustments:] sex, asthma study intervention group, birth weight, breastfeeding for at least 6 mo, parental obesity status, ethnicity, smoking in pregnancy and father’s education, total energy intake (food intake in g only); [underlined: Funding:] The National Health and Medical Research Council of Australia; Cooperative Research Centre for Asthma; New South Wales Department of Health; Children’s Hospital Westmead; University of Sydney, Faculty of Medicine; Commonwealth Department of Health and Aging
Garden, 2012 (https://pubmed.ncbi.nlm.nih.gov/23201761/)^29^; PCS, CAPS, Australia; [underlined: Analytic N] = 298 (Excluded participants who were not still participating in the study at 11.5 y or did not have dietary data.); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race and/or ethnicity:] NR (Australian born mother: 74%, Australian born father: 69%; Child's grandparents ethnicity/country of birth: Caucasian: ~54%, European: ~9%, Middle Eastern/Indian/Asian: ~12%, Undefined: ~25%); [underlined: Maternal education:] 52% tertiary educated; [underlined: Other SEP measure(s):] Full-time employment: Mother: 49%, Father: 87%; [underlined: Maternal age:] 29.0 (5.1) y; [underlined: Milk feeding practices:] BF duration: 0 to <3 mo: 40%, 3 to <6 mo: 16.8%, ≥6 mo: 43.2%; [underlined: Child sex (female):] 49%; [underlined: Birth weight:] 100% ≥2.5 kg; [underlined: Gestational age:] 100% ≥36 wk; [underlined: Other relevant characteristics:] Secondary analysis of RCT (testing intervention of house dust mite avoidance and omega-3 supplementation); all children recruited at increased risk of developing asthma | [underlined: Exposure(s) and comparator(s):]; Confectionary (chocolate, jellies, energy bars): Continuous (amounts); [underlined: Dietary assessment methods:] Parent/caregiver completed 3-d weighed food record (2 weekdays and 1 weekend day); [underlined: Age(s) at dietary assessment:] 18 mo; [underlined: Amounts consumed:] See results for intake data; [underlined: Outcome(s):] BMI trajectory; [underlined: Outcome assessment methods:] Weight and height measured by study nurses. Three BMI trajectories defined using latent basis growth mixture model in relationship to CDC percentiles, stratified by sex.; [underlined: Age(s) at outcome assessment:] 1, 3, 6, 9, 12, 18 mo, 2–5 y (every 6 mo), 8 y, 11.5 y | [underlined: BMI trajectory @ birth-11.5 y (median intake at 18 mo by trajectory group)]; Boys: normal trajectory: 1.3 g, early and persistent trajectory: 3.3 g, late BMI increase:; 4.0 g, p=0.41; Girls: normal trajectory: 4.0 g, early and persistent trajectory: 3.8 g, late BMI increase:; 3.3 g, p=0.99; Results analyzed by % of total energy were similar. | [underlined: Key confounders accounted for:] SEP; sex; race/ethnicity; milk feeding practices; baseline anthropometry (types and amounts, multinomial regression only).; [underlined: Key confounders NOT accounted for:] gestational age (types and amounts).; [underlined: Model adjustments:] dietary intervention group, BF, parental obesity, ethnicity, smoking during pregnancy, father's education status (types and amounts, multinomial regression only); [underlined: Funding:] National Health and Medical Research Council of Australia
Mahoney, 2018 (https://pubmed.ncbi.nlm.nih.gov/29607793/)^27^; PCS, Born in Bradford 1000, U.K.; [underlined: Analytic N] = 12 mo: 722; 18 mo: 779 (Excluded participants with multiple births, missing child dietary data or outcome data, and not of White British or Pakistani ethnicity); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race and/or ethnicity:] Pakistani: ~56%, White British: ~44%; [underlined: Maternal education:] NR; [underlined: Other SEP measure(s):] NR; [underlined: Maternal age:] NR; [underlined: Milk feeding practices:] NR; [underlined: Child sex (female):] NR; [underlined: Birth weight:] 3,234.15 (521.97) g; [underlined: Gestational age:] NR | [underlined: Exposure(s) and comparator(s):] Sweet snacks, including cakes, biscuits, chocolate, sweets: ≤ vs > Median frequency; [underlined: Dietary assessment methods:] FFQ completed by parents; [underlined: Age(s) at dietary assessment:] 12, 18 mo; [underlined: Amounts consumed:] Frequency at 12, 18 mo, respectively (Median, IQR): 0.6 (0.3, 1.1) x/d, 3.0 (2.0, 4.0) x/d; [underlined: Outcome(s):] BMIZ; [underlined: Outcome assessment methods:] Height, weight measured by trained researchers. Age- and sex-adjusted BMI calculated based on WHO 2006 standards.; [underlined: Age(s) at outcome assessment:] 36 mo | [underlined: BMIZ @ 36 mo (β (95% CI))]; Intake @ 12 mo: > vs ≤ 0.6/d: −0.05 (−0.21, 0.11), p=0.54; Intake @ 18 mo: > vs ≤ 3.0/d: 0.00 (−0.16, 0.15), p=0.99 | [underlined: Key confounders accounted for:] Sex; race and/or ethnicity; [underlined: Key confounders NOT accounted for:] SEP; milk feeding practices; gestational age; baseline anthropometry; [underlined: Model adjustments:] Ethnicity, sex, birth weight, other key indicator food groups (formula milk; commercial savoury baby foods; commercial sweet baby foods; chips, roast and potato shapes; processed meat products; vegetables; fruit; cakes, biscuits, chocolate and sweets; crisps and savoury snacks; sugar-sweetened drinks; pure fruit juice; low-sugar drinks; water); [underlined: Funding:] NIHR
[underlined: Moore, 2019]^40^; PCS, Nurture, U.S.; [underlined: Analytic N] = 466 (Reasons for attrition NR); [underlined: Adequately powered:] NR; [underlined: Participant Characteristics] (Mean (SD) unless otherwise noted); [underlined: Race and/or ethnicity:] Black: 71.5%, White: 19.2%, Other: 8.9%; Latina: 6.5%; (Child race and/or ethnicity: Black: 68.6%, White: 15.0%, White: 14.9%, Latina: 8.9%); [underlined: Maternal education:] ≤ HS diploma: 47.8%; Some college: 30.3%; College graduate: 15.5%; Graduate degree: 6.3%; [underlined: Other SEP measure(s):] Household income: ≤$20,000: 55.4%, $20,000–40,000: 19.1%, >$40,000: 16.7%; [underlined: Maternal age:] 27.1 (5.8) y; [underlined: Milk feeding practices:] BF duration: 14.7 (18.2) wk; [underlined: Child sex (female):] 49%; [underlined: Birth weight for gestational age z score:] −0.31 (0.9); [underlined: Gestational age:] 100% ≥37 wk | [underlined: Exposure(s) and comparator(s):] Sweets (cookies, cake, or candy): never, sometimes, often; [underlined: Dietary assessment methods:] Infant feeding questionnaire from IFPS II and FITS completed by mother: home visit (3, 6, 9, 12 mo); interactive voice response telephone calls (1, 2, 4, 5, 7, 8, 10, 11 mo); [underlined: Age(s) at dietary assessment:] 1–12 mo (monthly); [underlined: Amounts consumed:] Frequency, median (IQR): 0–3 mo: 0.0 x/d (0.0, 0.0), 4–6 mo: 0.0 x/d (0.0, 0.0), 7–9 mo: 0.0 x/d (0.0, 1.0), 10–12 mo: 0.7 x/d (0.0, 1.7); [underlined: Outcome(s):] WLZ; [underlined: Outcome assessment methods:] Weight and length were measured by study personnel. Age- and sex-specific WLZ calculated using WHO reference standards.; [underlined: Age(s) at outcome assessment:] 3 mo, 6 mo, 9 mo, 12 mo | [underlined: WLZ @ 6 mo (β (SE))]; Sweets at 4–6 mo; Sometimes vs Never (ref): 0.11 (0.12), p=NS; Often vs Never (ref): −0.46 (0.17), p<0.01; [underlined: WLZ @ 9 mo (β (SE))]; Sweets at 7–9 mo; Sometimes vs Never (ref): −0.09 (0.14), p=NS; Often vs Never (ref): 0.48 (0.18), p<0.01; [underlined: WLZ @ 12 mo (β (SE))]; Sweets at 10–12 mo; Sometimes vs Never (ref): 0.04 (0.14), p=NS; Often vs Never (ref): 0.53 (0.18), p<0.01; Sweets (often vs never) by Time interaction: p<0.01 | [underlined: Key confounders accounted for:] SEP; sex; race and/or ethnicity; milk feeding practices; gestational age; [underlined: Key confounders NOT accounted for:] baseline anthropometry; [underlined: Model adjustments:] birth weight-for-gestational age z-scores, total weeks of any breastfeeding; [underlined: Funding:] NIH

a Abbreviations: @: at; β: beta; BF: breastfeeding; BMI: body mass index; CAPS: Childhood Asthma Prevention Study; CDC: Centers for Disease Control and Prevention; CI: confidence interval; d: day; EBF: exclusive breastfeeding; FF: formula feeding; FFQ: food frequency questionnaire; g: gram; HS: high school; IQR: interquartile range; kg: kilogram; mo: month; NR: not reported; PCS: prospective cohort study; RCT: randomized controlled trial; ref: reference; RR: risk ratio; SD: standard deviation; SE: standard error; SEP: socioeconomic position; U.K.: United Kingdom; U.S.: United States; WC: waist circumference; WHO: World Health Organization; WIC: Special Supplemental Nutrition Program for Women, Infants, and Children; wk: week; WLZ: weight-for-length z-score; x: times; y: year

Table 56 Risk of bias for observational studies examining consumption of food sources of added sugars and growth, body composition, and risk of obesity ^a^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Amaro-Rivera, 2019^1^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Garden, 2011^30^ | SOME CONCERNS | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Garden 2012^29^ | SOME CONCERNS | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Mahoney, 2018^27^ | HIGH | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Moore, 2019^40^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH

a Possible ratings of low, some concerns, high, very high, no information, or not applicable determined using the "Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)" tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602. ) *Low risk of bias except for concerns about uncontrolled confounding.