# Methods

The Committee used NESR’s methodology to conduct this systematic review. NESR’s methodology is described in detail in its methodology manual, * as well as in the Committee’s Scientific Report. ^†^ This section presents an overview of the specific methods used to answer the systematic review question: What is the relationship between complementary feeding and growth, body composition, and risk of obesity?

* USDA Nutrition Evidence Systematic Review Branch. USDA Nutrition Evidence Systematic Review: Methodology Manual. February 2023. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: https://nesr.usda.gov/methodology-overview

† 2025 Dietary Guidelines Advisory Committee. 2024. Scientific Report of the 2025 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Health and Human Services and Secretary of Agriculture. U.S. Department of Health and Human Services. 10.52570/DGAC2025

This systematic review is an update to existing NESR systematic reviews completed as part of the Pregnancy and Birth to 24 Months Project by the Complementary Feeding Technical Expert Collaborative, ^‡^,^§^ which included evidence published from January 1980 to July 2016. This update synthesized all of the eligible studies from January 1980 to May 2023 to develop and grade conclusion statements, according to the methods described below. This means that all of the eligible articles from the existing reviews and the newly published articles were resynthesized as one body of evidence.

‡ English LK, Obbagy JE, Wong YP, . Timing of Introduction of Complementary Foods and Beverages and Growth, Size, and Body Composition: A Systematic Review. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review; 2019. 10.52570/NESR.PB242018.SR0305.

§ English LK, Obbagy JE, Wong YP, . Types and Amounts of Complementary Foods and Beverages and Growth, Size, and Body Composition: A Systematic Review. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review; 2019. 10.52570/NESR.PB242018.SR0306.

In addition, this review is related to 2 systematic reviews with meta-analysis conducted by the Committee to answer the systematic review questions: “What is the relationship between 100% juice consumption and growth, body composition, and risk of obesity?” ** and “What is the relationship between sugar-sweetened beverages consumption and growth, body composition, and risk of obesity?” ^††^ These systematic reviews with meta-analysis examined 100% juice and sugar-sweetened beverage (SSB) consumption, respectively, across the lifespan from infancy through adulthood. Relevant articles from the present systematic review on complementary feeding were included and synthesized in these 2 systematic reviews with meta-analysis and contributed to the review of evidence from infancy through adolescence.

** Deierlein AL, Raynor HA, Andres A, . 100% Juice and Growth, Body Composition, and Risk of Obesity: A Systematic Review with Meta-Analysis U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review; 2024. 10.52570/NESR.DGAC2025.SR05

†† Deierlein AL, Raynor HA, Byrd-Bredbenner C, . Sugar-Sweetened Beverages and Growth, Body Composition, and Risk of Obesity: A Systematic Review with Meta-Analysis. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review; 2024. 10.52570/NESR.DGAC2025.SR23.

## Develop a protocol

A systematic review protocol is the plan for how NESR’s methodology will be used to conduct a specific systematic review and is established by the Committee, a priori, before any evidence is reviewed. The protocol is designed to capture the most appropriate and relevant body of evidence to answer the systematic review question. Development of the protocol involves discussion of the strengths and limitations of various methodological approaches relevant to the question, which then inform subsequent steps of the systematic review process. The protocol describes all of the methods that will be used throughout the systematic review process. Additionally, the protocol includes the following components, which are tailored to each systematic review question: the analytic framework, the inclusion and exclusion criteria, and the synthesis plan. The Committee used the analytic framework and the inclusion and exclusion criteria from the existing review and made adjustments to the protocol, as needed. Differences in the inclusion and exclusion criteria between existing and updated reviews are documented in Appendix 3.

The protocol was posted online (https://nesr.usda.gov/protocols) for the public to view and comment on. Revisions to the systematic review protocol were made during the review process. These amendments are documented in Table 2.

Table 2 Protocol revisions

Date | Protocol revision | Description
March 2024 | Inclusion and exclusion criteria were added for study directness, specifying that randomized and non-randomized controlled trials not directly designed to measure the effects of complementary feeding on growth, body composition, and risk of obesity would be excluded. | This revision was made to enable focus on a stronger body of evidence that was more directly designed to answer the research question. This revision was made at the beginning of evidence synthesis.
April 2024 | Exclusion criteria were added for interventions and exposures, specifying that studies that did not address 100% juice, fruit, vegetables, grains, protein foods, dairy and fortified soy alternatives, or food/beverage sources of added sugars would be excluded | This revision was made to enable focus on evidence more directly designed to answer the research question and in consideration of project workload and timelines. This revision was made at the beginning of evidence synthesis.
April 2024 | The timing of the first introduction of any complementary food or beverage was removed as an intervention or exposure in this systematic review | This revision was made in consideration of project workload and timelines. This intervention/exposure has an existing conclusion statement that was graded as moderate, based on studies published from 1980 to 2016. Therefore, it was determined to be lower priority to update. This revision was made before evidence synthesis.

## Develop an analytic framework

An analytic framework visually represents the overall scope of the systematic review question and depicts the contributing elements that were examined and evaluated. It presents the core elements of each systematic review question, including the Population (i.e., those who experience the intervention/exposure and/or outcome), Intervention and/or exposure (i.e., the independent variable of interest), Comparator (i.e., the alternative being compared to the intervention or exposure), and Outcome(s). Definitions for key terms are also included because they provide the basis for how concepts are operationalized throughout the review. The Committee identified key confounders based on their knowledge of nutrition and health research and experience as subject matter experts. Key confounders are participant characteristics, such as demographics, health status, and diet and lifestyle behaviors, and/or other factors related to both the intervention/exposure and the outcome of interest that may impact the relationships of interest. Key confounders were considered during review and evaluation of the evidence, particularly during the risk of bias assessment of non-randomized and observational studies.

Figure 1 is the analytic framework for the systematic review. The interventions or exposures of interest are the timing of the first introduction of a specific type of complementary food or beverage (further subdivided by the following food and beverage groups: fruit, including 100% fruit juice, vegetables, grains, protein foods, dairy and fortified soy alternatives, and food/beverage sources of added sugars) and types and amounts of complementary foods and beverages (further subdivided by the following food and beverage groups: fruit, including 100% fruit juice, vegetables, grains, protein foods, dairy and fortified soy alternatives, and food/beverage sources of added sugars) in infants and young children (birth up to 24 months). The comparators are different timing of the first introduction of a specific type of complementary food or beverage and different amount of the same complementary food or beverage or different type of complementary food or beverage. The outcomes are: Growth (in infants, young children, children, adolescents) including: height, length/stature-for-age, weight, weight-for-age, stunting, failure to thrive, wasting, BMI-for-age, weight-for-length/stature, body circumferences (arm, neck, thigh), head circumference; Body composition (in infants, young children, children, adolescents, adults, older adults) including: skinfold thickness, fat mass, ectopic fat, fat-free mass or lean mass, waist circumference, waist-to-hip-ratio; Risk of obesity (in children, adolescents, adults, older adults) including: BMI, overweight and obesity, underweight, normal/healthy weight. The key confounders are socioeconomic position, sex, race and/or ethnicity, milk feeding practices (human milk, infant formula, or both), gestational age, and baseline anthropometry.

Figure 1 Analytic framework for the systematic review question: What is the relationship between complementary feeding and growth, body composition, and risk of obesity?

Population | Intervention/exposure | Comparator | Outcomes | Key confounders
Infants and young children (birth up to 24 months) | Timing of the first introduction of a specific type of complementary food or beverage (CFB):; 1) Fruit, including 100% fruit juice; 2) Vegetables; 3) Grains; 4) Protein foods; 5) Dairy and fortified soy alternatives; 6) Food/beverage sources of added sugars | Different timing of the first introduction of a specific type of CFB | Growth (in infants, young children, children, adolescents); - Height, length/stature-for-age; - Weight, weight-for-age; - Stunting, failure to thrive, wasting; - BMI-for-age, weight-for-length/stature; - Body circumferences (arm, neck, thigh); - Head circumference; Body composition (in infants, young children, children, adolescents, adults, older adults); - Skinfold thickness; - Fat mass, ectopic fat; - Fat-free, lean mass; - Waist circumference, waist-to-hip ratio; Risk of obesity (in children, adolescents, adults, older adults); - BMI; - Overweight and obesity; - Underweight; - Normal/healthy weight | - Socioeconomic position; - Sex; - Race and/or ethnicity; - Milk feeding practices (human milk, infant formula, or both); - Gestational age; - Baseline anthropometry
Infants and young children (birth up to 24 months) | Types and amounts of CFB:; 1) Fruit, including 100% fruit juice; 2) Vegetables; 3) Grains; 4) Protein foods; 5) Dairy and fortified soy alternatives; 6) Food/beverage sources of added sugars | Different amount of the same CFB; Different type of CFB | | - Socioeconomic position; - Sex; - Race and/or ethnicity; - Milk feeding practices (human milk, infant formula, or both); - Gestational age; - Baseline anthropometry

Synthesis organization:

I. Intervention/exposure: Timing of the first introduction of a specific type of complementary food or beverage: 1) Fruit, including 100% fruit juice; 2) Vegetables; 3) Grains; 4) Protein foods; 5) Dairy and fortified soy alternatives; 6) Food/beverage sources of added sugars
  a. Outcome: Growth; Body composition; Risk of obesity
II. Intervention/exposure: Types and amounts of complementary food or beverage: 1) Fruit, including 100% fruit juice; 2) Vegetables; 3) Grains; 4) Protein foods; 5) Dairy and fortified soy alternatives; 6) Food/beverage sources of added sugars
  a. Outcome: Growth; Body composition; Risk of obesity

Key definitions:

[underlined: Complementary feeding]: The process that starts when human milk or infant formula is complemented by other foods and beverages. The complementary feeding period typically continues to 24 months as the young child transitions to family foods.

[underlined: Complementary foods and beverages (CFB)]: Foods and beverages (liquids, semisolids, and solids) other than human milk or infant formula provided to an infant or young child to provide nutrients and energy.

## Develop inclusion and exclusion criteria

The inclusion and exclusion criteria provide an objective, consistent,and transparent framework for determining which articles to include in the systematic review (Table 3). These criteria ensure that the most relevant and appropriate body of evidence is identified for the systematic review question, and that the evidence reviewed is *:

- Applicable to the U.S. population of interest
- Relevant to Federal public health nutrition policies and programs
- Rigorous from a scientific perspective

* USDA Nutrition Evidence Systematic Review Branch. USDA Nutrition Evidence Systematic Review: Methodology Manual. February 2023. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: https://nesr.usda.gov/methodology-overview

Table 3 Inclusion and exclusion criteria

Category | Inclusion Criteria | Exclusion Criteria
Study design | - Randomized controlled trials; - Non-randomized controlled trials^†^; † Including quasi-experimental and controlled before-and-after studies; - Prospective cohort studies; - Retrospective cohort studies; - Nested case-control studies | - Uncontrolled trials^‡^; ‡ Including uncontrolled before-and-after studies; - Case-control studies; - Cross-sectional studies; - Ecological studies; - Narrative reviews; - Systematic reviews; - Meta-analyses; - Modeling and simulation studies
Publication date | - January 1980 – May 2023^§^; § This review update date range encompasses the original systematic review date range, which included articles published from January 1980 to July 2016 | - Before January 1980, after May 2023
Population: Study participants | - Human | - Non-human
Population: Life stage | - At intervention or exposure:; ○ Infants and young children (birth up to months); - At outcome:; ○ Infants and young children (birth up to 24 months); ○ Children and adolescents (2 up to 19 years); ○ Adults and older adults (19 years and older) | - At intervention or exposure:; ○ Children and adolescents (2 up to 19 years); ○ Adults and older adults (19 years and older)
Population: Health status | - Studies that [underlined: exclusively] enroll participants not diagnosed with a disease^*^; * Studies that enroll participants who are at risk for chronic disease were included; - Studies that enroll [underlined: some] participants:; ○ diagnosed with a disease;; ○ with severe undernutrition, failure to thrive/underweight, stunting, or wasting;; ○ born preterm, ^†^ with low birth weight,^‡^ and/or small for gestational age; † Gestational age <37 weeks and 0/7 days; ‡ Birth weight <2500g; ○ and/or hospitalized for an illness, injury, or surgery | - Studies that [underlined: exclusively] enroll participants:; ○ diagnosed with a disease;^§^; § Studies that exclusively enroll participants with obesity were included; ○ with severe undernutrition, failure to thrive/underweight, stunting, or wasting;; ○ born preterm,** with low birth weight,^††^ and/or small for gestational age;; ○ and/or hospitalized for an illness, injury, or surgery
Intervention/exposure | - Timing of the first introduction of a specific type of complementary food or beverage (CFB)^**^; ** Complementary foods and beverages (CFB) are defined as foods and beverages (liquids, semisolids, and solids) other than human milk or infant formula provided to an infant or young child to provide nutrients and energy; ○ Fruit, including 100% fruit juice; ○ Vegetables; ○ Grains; ○ Protein foods; ○ Dairy and fortified soy alternatives; ○ Food/beverage sources of added sugars; - Types and amounts of CFB; ○ Fruit, including 100% fruit juice; ○ Vegetables; ○ Grains; ○ Protein foods; ○ Dairy and fortified soy alternatives; ○ Food/beverage sources of added sugars | - Isolated consumption of human milk, infant formulas (e.g., milk-based, soy, partially hydrolyzed, extensive-hydrolyzed, amino acid based), or vitamin and mineral supplements (e.g., iron drops); - Dietary patterns; - Interventions/exposures that do not address any of the following (including interventions/exposures of multiple food groups examined jointly): fruit, including 100% fruit juice, vegetables, grains, protein foods, dairy and fortified soy alternatives, and food/beverage sources of added sugars; - Type and/or amount of food or beverage not described; - Timing of the first introduction of any CFB
Comparator | - Different timing of the first introduction of a specific type of CFB; - Different types and amounts of CFB; ○ Consumption of a different amount of the same CFB; ○ Consumption of a different type of CFB | - No comparator
Outcomes | Growth (in infants, young children, children, adolescents); - Height, length/stature-for-age; - Weight, weight-for-age; - Stunting, failure to thrive, wasting; - BMI-for-age, weight-for-length/stature; - Body circumferences (arm, neck, thigh); - Head circumference; Body composition (in infants, young children, children, adolescents, adults, older adults); - Skinfold thickness; - Fat mass, ectopic fat; - Fat-free mass, lean mass; - Waist circumference, waist-to-hip ratio; Risk of obesity (in children, adolescents, adults, older adults); - BMI; - Overweight and obesity; - Underweight; - Healthy/normal weight | - Not applicable
Directness of experimental studies | - Randomized or non-randomized controlled trials designed to examine growth, body composition and/or risk of obesity as a primary outcome | - Randomized or non-randomized controlled trials that were not designed to examine growth, body composition, and/or risk of obesity as a primary outcome (i.e., designed to examine another primary outcome).
Publication status | - Peer-reviewed articles published in research journals | - Non-peer-reviewed articles, unpublished data or manuscripts, pre-prints, reports, editorials, retracted articles, and conference abstracts or proceedings
Language | - Published in English | - Not published in English
Country^*^; * The classification of countries on the Human Development Index (HDI) is based on the UN Development Program Human Development Report Office (http://hdr.undp.org/en/data) for the year the study intervention occurred or data were collected. If the study does not report the year(s) in which the intervention/exposure data were collected, the HDI classification for the year of publication is applied. Studies conducted prior to 1990 are classified based on 1990 HDI classifications. If the year is more recent than the available HDI values, then the most recent HDI classifications are used. If a country is not listed in the HDI, then the current country classification from the World Bank is used (The World Bank Country and Lending Groups, available from: https://datahelpdesk.worldbank.org/knowledgebase/articles/906519-world-country-and-lending-groups) | - Studies conducted in countries classified as high or very high on the Human Development Index the year(s) the intervention/exposure data were collected | - Studies conducted in countries classified as medium or low on the Human Development Index the year(s) the intervention/exposure data were collected

## Search for and screen studies

NESR librarians, in collaboration with NESR analysts and the Committee, used the analytic framework and inclusion and exclusion criteria to develop a comprehensive literature search strategy. The literature search strategy included selecting and searching the appropriate bibliographic databases, translating search using syntax appropriate for the databases being searched, and employing search refinements, such as search filters. For existing reviews, search strategies were updated, as appropriate, for each database. The full literature search is documented in Appendix 4.

The results of all electronic database searches, after removal of duplicates, were screened independently by 2 NESR analysts using a step-wise process by reviewing titles, abstracts, and full-texts to determine which articles meet the inclusion criteria. Manual searching was conducted to find peer-reviewed published articles not identified through the electronic database search. These articles were also screened independently by 2 NESR analysts at the abstract and full-text levels.

## Extract data and assess the risk of bias

NESR analysts extracted all essential data from each included article to describe key characteristics of the available evidence, such as the author, publication year, cohort/trial name, study design, population life stage at intervention/exposure and outcome, intervention/exposure and outcome assessment methods, and outcomes. One NESR analyst extracted the data and a second NESR analyst reviewed the extracted data for accuracy. Each article included in the systematic review underwent a formal risk of bias assessment, with 2 NESR analysts independently completing the risk of bias assessment using the tool that is appropriate for the study design. * ^†^ ^‡^

* Sterne JAC, Savović J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ 2019; 366: l4898.doi:10.1136/bmj.l4898 31462531

† Sterne JAC, Hernán MA, Reeves BC, . ROBINS-I: a tool for assessing risk of bias in non-randomized studies of interventions. BMJ 2016; 355; i4919; doi: 10.1136/bmj.i4919 27733354

‡ Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi:10.1016/j.envint.2024.108602

## Synthesize the evidence

The Committee described, compared, and combined the evidence from all included studies to answer the systematic review question. ^§^ Synthesis of the body of evidence involved identifying overarching themes or key concepts from the findings, identifying and explaining similarities and differences between studies, and determining whether certain factors impact the relationships being examined, which includes potential causes of heterogeneity across all included evidence.

§ USDA Nutrition Evidence Systematic Review Branch. USDA Nutrition Evidence Systematic Review: Methodology Manual. February 2023. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: https://nesr.usda.gov/methodology-overview

Extracted data and risk of bias assessments for all included studies were tabulated to visually display results and facilitate synthesis. During synthesis, the Committee considered the effect direction, magnitude, and statistical significance of the results reported across the articles included in the body of evidence. The evidence was synthesized qualitatively without meta-analysis of effect estimates, statistical pooling or conversion of data, or quantitative tests of heterogeneity.

The synthesis plan for this review was designed with the end-use in mind, to inform the Committee’s advice to HHS and USDA regarding dietary guidance across life stages. The first level of synthesis organization was by intervention/exposure (timing of the first introduction of a specific type of complementary food and beverage; types and amounts of complementary foods and beverages). The evidence was further organized by food and/or beverage groups (fruit, including 100% fruit juice; vegetables; grains; protein foods; dairy and fortified soy alternatives; food/beverage sources of added sugars). Then, within each of the intervention/exposure groups, the evidence was organized by similar outcomes (growth; body composition; risk of obesity) based on the available evidence. Depending on the available evidence for types and amounts of complementary foods and beverages, a final level of synthesis organization was going to be according to age at intervention/exposure.

In addition to the present systematic review on complementary feeding, 2 systematic reviews with meta-analysis were conducted on the related topics of SSB intake and growth, body composition, and risk of obesity^*^ and 100% juice intake and growth, body composition, and risk of obesity^†^ across the lifespan, including infants and young children. Results of the meta-analyses that were relevant to complementary feeding in infants and young children (up to 24 months) were considered during the synthesis of the evidence and documented in the complementary feeding and growth, body composition, and risk of obesity systematic review.

* Deierlein AL, Raynor HA, Byrd-Bredbenner C, . Sugar-Sweetened Beverages and Growth, Body Composition, and Risk of Obesity: A Systematic Review with Meta-Analysis. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review; 2024. 10.52570/NESR.DGAC2025.SR05

† Deierlein AL, Raynor HA, Andres A, . 100% Juice and Growth, Body Composition, and Risk of Obesity: A Systematic Review with Meta-Analysis U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review; 2024. 10.52570/NESR.DGAC2025.SR05

## Develop conclusion statements and grade the evidence

After the Committee synthesized the body of evidence, they drafted conclusion statements. A conclusion statement is one or more summary statements carefully constructed to answer the systematic review question. Each conclusion statement reflects the evidence reviewed, as outlined in the analytic framework (e.g., PICO elements) and synthesis plan, and does not take evidence from other sources into consideration. Conclusion statements do not draw implications and should not be interpreted as dietary guidance. The Committee reviewed, discussed, and revised the conclusion statements until they reached agreement on wording that accurately reflected the body of evidence.

The Committee then graded the strength of the evidence underlying each conclusion statement. They did this using NESR’s predefined criteria, based on 5 grading elements: consistency, precision, risk of bias, directness and generalizability of the evidence. Study design and publication bias were also considered. ^‡^

- [underlined: Consistency]: Consistency considers the degree of similarity in the direction and magnitude of effect across the body of evidence. This element also considers whether differences across the results can be explained by variations in study designs and methods.
- [underlined: Precision]: Precision considers the degree of certainty around an effect estimate for a given outcome. This element considers measures of variability, such as the width and range of confidence intervals, the number of studies, and sample sizes, within and across studies.
- [underlined: Risk of bias]: Risk of bias considers the likelihood that systematic errors resulting from the design and conduct of the studies could have impacted the accuracy of the reported results across the body of evidence.
- [underlined: Directness]: Directness considers the extent to which studies are designed to directly examine the relationship among the interventions/exposures, comparators, and outcome(s) of primary interest in the systematic review question.
- [underlined: Generalizability]: Generalizability considers whether the study participants, interventions and/or exposures, comparators, and outcomes examined in the body of evidence are applicable to the U.S. population of interest for the review.

‡ Spill MK, English LK, Raghavan R, . Perspective: USDA Nutrition Evidence Systematic Review Methodology: Grading the Strength of Evidence in Nutrition- and Public Health-Related Systematic Reviews. Adv Nutr. 2022 Aug 1;13(4):982–991. doi: 10.1093/advances/nmab147 34918032

The Committee assigned a grade to each conclusion statement (i.e., strong, moderate, limited, or grade not assignable). The grade communicates the strength of the evidence supporting a specific conclusion statement to decision makers and stakeholders. A conclusion statement can receive a grade of Strong, Moderate, or Limited, and if insufficient or no evidence is available to answer a systematic review question, then no grade is assigned (i.e., Grade Not Assignable) (Table 4). The overall grade is not based on a predefined formula for scoring or tallying ratings of each element. Rather, each overall grade reflects the expert group’s thorough consideration of all of the grading elements, as they each relate to the specific nuances of the body of evidence under review.

Table 4 Definitions of NESR grades

Grade | Definition
Strong | The conclusion statement is based on a strong body of evidence as assessed by consistency, precision, risk of bias, directness, and generalizability. The level of certainty in the conclusion is strong, such that if new evidence emerges, modifications to the conclusion are unlikely to be required.
Moderate | The conclusion statement is based on a moderate body of evidence as assessed by consistency, precision, risk of bias, directness, and generalizability. The level of certainty in the conclusion is moderate, such that if new evidence emerges, modifications to the conclusion may be required.
Limited | The conclusion statement is based on a limited body of evidence as assessed by consistency, precision, risk of bias, directness, and generalizability. The level of certainty in the conclusion is limited, such that if new evidence emerges, modifications to the conclusion are likely to be required.
Grade Not Assignable | A conclusion statement cannot be drawn due to either a lack of evidence, or evidence that has severe limitations related to consistency, precision, risk of bias, directness, and generalizability.

## Recommend future research

The Committee identified and documented research gaps and methodological limitations throughout the systematic review process. These gaps and limitations are used to develop research recommendations that describe the research, data, and methodological advances that are needed to strengthen the body of evidence on a particular topic. Rationales for the necessity of additional or stronger research are also provided with the research recommendations.

## Peer review

This systematic review underwent external peer review in a process coordinated by staff from the National Institutes of Health (NIH). NIH staff identified potential peer reviewers through outreach to a variety of professional organizations to select academic reviewers from U.S. colleges and universities across the country with a doctorate degree, including MDs, and expertise specific to the questions being reviewed. All peer reviewers were external to the Dietary Guidelines process, and therefore, current Committee members or Federal staff who supported the Committee or the development of the Dietary Guidelines were not eligible to serve as peer reviewers.

The peer review process was anonymous and confidential in that the peer reviewers were not identified to the Committee members or NESR staff, and in turn, the reviewers were asked not to share or discuss the review with anyone. Peer reviewers were made aware that per USDA, Food and Nutrition Service (FNS) agency policy, all peer reviewer comments would be summarized and made public, but comments would not be attributed to a specific reviewer.

Peer review occurred after draft conclusion statements were discussed by the full Committee at its third, fourth, fifth, and sixth public meetings. NIH staff assigned and distributed the reviews to at least 2 peer reviewers based on area of expertise. Following peer review, the Committee reviewed and discussed comments and made revisions to the systematic review, as needed, based on the discussion.

## Health equity considerations

The Committee was charged by HHS and USDA to review all scientific questions with a health equity lens to ensure that the next edition of the Dietary Guidelines is relevant to people with diverse racial, ethnic, socioeconomic, and cultural backgrounds. The Committee made a number of health equity considerations throughout the NESR systematic review process. The Committee’s Scientific Report * includes a more detailed discussion of their approach to applying a health equity lens to their review of evidence, but examples include consideration of key confounders relevant to health equity and assessment of generalizability of the evidence.

* 2025 Dietary Guidelines Advisory Committee. 2024. Scientific Report of the 2025 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Health and Human Services and Secretary of Agriculture. U.S. Department of Health and Human Services. 10.52570/DGAC2025