# Appendix 5 Excluded articles

The existing systematic reviews^*^,^†^ for this question included 113 total articles. However, after applying the inclusion and exclusion criteria established for the update to that review, 90 articles were no longer eligible for inclusion (Table A 12). The majority of these articles were excluded based on the intervention or exposure, as the systematic review inclusion and exclusion criteria were updated to remove first introduction of any complementary food or beverage as an intervention or exposure in this systematic review.

* English LK, Obbagy JE, Wong YP, . Timing of Introduction of Complementary Foods and Beverages and Growth, Size, and Body Composition: A Systematic Review. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review; 2019. 10.52570/NESR.PB242018.SR0305.

† English LK, Obbagy JE, Wong YP, . Types and Amounts of Complementary Foods and Beverages and Growth, Size, and Body Composition: A Systematic Review. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review; 2019. 10.52570/NESR.PB242018.SR0306.

Table A 12 Excluded articles from the existing systematic reviews due to updated eligibility criteria

| Citation | Rationale
1 | Abraham EC, Godwin J, Sherriff A, Armstrong J. Infant feeding in relation to eating patterns in the second year of life and weight status in the fourth year. Public Health Nutr. 2012;15(9):1705–14. doi: 10.1017/S1368980012002686 22626031 | Intervention/exposure
2 | Agras WS, Kraemer HC, Berkowitz RI, Hammer LD. Influence of early feeding style on adiposity at 6 years of age. J Pediatr. 1990;116(5):805–9. doi: 10.1016/s0022-3476(05)82677-0 2329430 | Intervention/exposure
3 | Atkins LA, McNaughton SA, Campbell KJ, Szymlek-Gay EA. Iron intakes of Australian infants and toddlers: Findings from the Melbourne Infant Feeding, Activity and Nutrition Trial (InFANT) Program. Br J Nutr. 2016;115(2):285–93. doi: 10.1017/S0007114515004286 26571345 | Intervention/exposure
4 | Bainbridge RR, Mimouni FB, Landi T, Crossman M, Harris L, Tsang RC. Effect of rice cereal feedings on bone mineralization and calcium homeostasis in cow milk formula fed infants. J Am Coll Nutr. 1996;15:383–8. doi: 10.1080/07315724.1996.10718613 8829094 | Directness of experimental studies
5 | Baird J, Poole J, Robinson S, Milk feeding and dietary patterns predict weight and fat gains in infancy. Paediatr Perinat Epidemiol. 2008;22(6):575–86. doi: 10.1111/j.1365-3016.2008.00963.x 19000296 | Study design
6 | Baker JL, Michaelsen KF, Rasmussen KM, Sorensen TIA. Maternal prepregnant body mass index, duration of breastfeeding, and timing of complementary food introduction are associated with infant weight gain. Am J Clin Nutr. 2004;80(6):1579–88. doi: 10.1093/ajcn/80.6.1579 15585772 | Intervention/exposure
7 | Bammann K, Peplies J, De Henauw S, Early life course risk factors for childhood obesity: the IDEFICS case-control study. PloS One. 2014;9(2):e86914. doi: 10.1371/journal.pone.0086914 24551043 | Study design
8 | Barrera CM, Perrine CG, Li R, Scanlon KS. Age at Introduction to Solid Foods and Child Obesity at 6 Years. Child Obes. 2016;12(3):188–92. doi: 10.1089/chi.2016.0021 27058343 | Intervention/exposure
9 | Barton SJ, Howard PK, Rayens MK. The effects of infant feeding decisions on infant growth. J Spec Pediatr Nurs. 2002;7(2):64–70. doi: 10.1111/j.1744-6155.2002.tb00152.x 12061494 | Study design
10 | Bell LK, Golley RK, Daniels L, Magarey AM. Dietary patterns of Australian children aged 14 and 24 months, and associations with socio-demographic factors and adiposity. Eur J Clin Nutr. 2013;67(6):638–45. doi: 10.1038/ejcn.2013.23 23443830 | Intervention/exposure
11 | Burdette HL, Whitaker RC, Hall WC, Daniels SR. Breastfeeding, introduction of complementary foods, and adiposity at 5 y of age. Am J Clin Nutr. 2006;83(3):550–8. doi: 10.1093/ajcn.83.3.550 16522900 | Intervention/exposure
12 | Dagnelie PC, van Staveren WA. Macrobiotic nutrition and child health: results of a population-based, mixed-longitudinal cohort study in The Netherlands. Am J Clin Nutr. 1994;59(5 Suppl):1187s–96s. doi: 10.1093/ajcn/59.5.1187S 8172122 | Intervention/exposure
13 | Davidsson L, Mackenzie J, Kastenmayer P, Dietary fiber in weaning cereals: a study of the effect on stool characteristics and absorption of energy, nitrogen, and minerals in healthy infants. J Pediatr Gastroenterol Nutr. 1996;22(2):167–79. doi: 10.1097/00005176-199602000-00008 8642490 | Comparator
14 | de Beer M, Vrijkotte TG, Fall CH, van Eijsden M, Osmond C, Gemke RJ. Associations of infant feeding and timing of linear growth and relative weight gain during early life with childhood body composition. Int J Obes. 2015;39:586–92. doi: 10.1038/ijo.2014.200 | Intervention/exposure
15 | Dube K, Schwartz J, Mueller MJ, Kalhoff H, Kersting M. Complementary food with low (8%) or high (12%) meat content as source of dietary iron: a double-blinded randomized controlled trial. Eur J Nutr. 2010;49(1):11–8. doi: 10.1007/s00394-009-0043-9 19618230 | Directness of experimental studies
16 | Durmus B, Ay L, Duijts L, Infant diet and subcutaneous fat mass in early childhood: the Generation R Study. Eur J Clin Nutr. 2012;66:253–60. doi: 10.1038/ejcn.2011.174 21989323 | Intervention/exposure
17 | Durmus B, Heppe DH, Gishti O, General and abdominal fat outcomes in school-age children associated with infant breastfeeding patterns. Am J Clin Nutr. 2014;99(6):1351–8. doi: 10.3945/ajcn.113.075937 24622802 | Intervention/exposure
18 | Engelmann MD, Sandstrom B, Michaelsen KF. Meat intake and iron status in late infancy: an intervention study. J Pediatr Gastroenterol Nutr. 1998;26(1):26–33. doi: 10.1097/00005176-199801000-00005 9443116 | Directness of experimental studies
19 | Fairley L, Santorelli G, Lawlor DA, The relationship between early life modifiable risk factors for childhood obesity, ethnicity and body mass index at age 3 years: findings from the Born in Bradford birth cohort study. BMC Obes. 2015;2:9. doi: 10.1186/s40608-015-0037-5 26217524 | Intervention/exposure
20 | Fawzi WW, Forman MR, Levy A, Graubard BI, Naggan L, Berendes HW. Maternal anthropometry and infant feeding practices in Israel in relation to growth in infancy: the North African Infant Feeding Study. Am J Clin Nutr. 1997;65(6):1731–7. doi: 10.1093/ajcn/65.6.1731 9174468 | Intervention/exposure
21 | Ferris AG, Laus MJ, Hosmer DW, Beal VA. The effect of diet on weight gain in infancy. Am J Clin Nut. 1980;33(12):2635–42. doi: 10.1093/ajcn/33.12.2635 | Intervention/exposure
22 | Forsyth JS, Ogston SA, Clark A, Florey CD, Howie PW. Relation between early introduction of solid food to infants and their weight and illnesses during the first two years of life. BMJ. 1993;306(6892):1572–6. doi: 10.1136/bmj.306.6892.1572 8329916 | Intervention/exposure
23 | Friel JK, Gibson RS, Kawash GF, Watts J. Dietary zinc intake and growth during infancy. J Pediatr Gastroenterol Nutr. 1985;4(5):746–51. doi: 10.1097/00005176-198510000-00011 4045633 | Intervention/exposure
24 | Gibbs BG, Forste R. Socioeconomic status, infant feeding practices and early childhood obesity. Pediatr Obes. 2014;9(2):135–46. doi: 10.1111/j.2047-6310.2013.00155.x 23554385 | Intervention/exposure
25 | Golley, RK, Smithers, LG, Mittinty, MN, Emmett P, Northstone K, Lynch JW. Diet quality of U.K. infants is associated with dietary, adiposity, cardiovascular, and cognitive outcomes measured at 7-8 years of age. J Nutr. 2013;143(10):1611–7. doi: 10.3945/jn.112.170605 23946339 | Intervention/exposure
26 | Griffiths LJ, Hawkins SS, Cole TJ, Dezateux C. Risk factors for rapid weight gain in preschool children: findings from a UK-wide prospective study. Int J Obes. 2010;34(4):624–32. doi: 10.1038/ijo.2010.10 | Intervention/exposure
27 | Griffiths LJ, Smeeth L, Sherburne Hawkins S, Cole TJ, Dezateux, C. Effects of infant feeding practice on weight gain from birth to 3 years. Arch Dis Child. 2009;94(8):577–82. doi: 10.1136/adc.2008.137554 19019884 | Intervention/exposure
28 | Grote V, Schiess SA, Closa-Monasterolo R, The introduction of solid food and growth in the first 2 y of life in formula-fed children: analysis of data from a European cohort study. Am J Clin Nutr. 2011;94(6 Suppl):1785s–93s. doi: 10.3945/ajcn.110.000810 21918213 | Intervention/exposure
29 | Gungor DE, Paul IM, Birch LL, Bartok CJ. Risky vs rapid growth in infancy: refining pediatric screening for childhood overweight. Arch Pediatr Adolesc Med. 2010;164:1091–7. doi: 10.1001/archpediatrics.2010.238 21135336 | Intervention/exposure
30 | Harendra de Silva DG, Rajindrajith S, Pathmeswaran A, Karunasekera W. An intervention study to monitor weight gain in infants using a home based complementary food recipe and a hand blender. Ceylon Med J. 2007;52(3):79–83. doi: 10.4038/cmj.v52i3.963 18020022 | Country
31 | Haschke F, van't Hof MA. Euro-Growth references for breast-fed boys and girls: influence of breast-feeding and solids on growth until 36 months of age. Euro-Growth Study Group. J Pediatr Gastroenterol Nutr. 2000;31 Suppl 1:S60–71. doi: 10.1097/00005176-200007001-00006 10896090 | Intervention/exposure
32 | Hawkins SS, Cole TJ, Law C. An ecological systems approach to examining risk factors for early childhood overweight: findings from the UK Millennium Cohort Study. J Epidemiol Community Health. 2009;63:147–55. doi: 10.1136/jech.2008.077917 18801795 | Intervention/exposure
33 | Heinig MJ, Nommsen LA, Peerson JM, Lonnerdal B, Dewey KG. Intake and growth of breast-fed and formula-fed infants in relation to the timing of introduction of complementary foods: the DARLING study. Davis Area Research on Lactation, Infant Nutrition and Growth. Acta Paediatr. 1993;82(12):999–1006. doi: 10.1111/j.1651-2227.1993.tb12798.x 8155936 | Intervention/exposure
34 | Hertrampf E, Olivares M, Pizarro F, Haemoglobin fortified cereal: a source of available iron to breast-fed infants. Eur J Clin Nutr. 1990;44(11):793–8.2086208 | Directness of experimental studies
35 | Hoffman DR, Theuer RC, Castaneda YS, Maturation of visual acuity is accelerated in breastfed term infants fed baby food containing DHA-enriched egg yolk. J Nutr. 2004;134(9):2307–13. doi: 10.1093/jn/134.9.2307 15333721 | Directness of experimental studies
36 | Huh SY, Rifas-Shiman SL, Taveras EM, Oken E, Gillman MW. Timing of solid food introduction and risk of obesity in preschool-aged children. Pediatrics. 2011;127(3):e544–51. doi: 10.1542/peds.2010-0740 21300681 | Intervention/exposure
37 | Hui LL, Nelson EA, Yu LM, Li AM, Fok TF. Risk factors for childhood overweight in 6- to 7-y-old Hong Kong children. Int J Obes Relat Metab Disord. 2003;27(11):1411–8. doi: 10.1038/sj.ijo.0802423 14574354 | Study design
38 | Iannotti LL, Zavaleta N, Leon Z, Caulfield LE. Growth and body composition of Peruvian infants in a periurban setting. Food Nutr Bull. 2009;30(3):245–53. doi: 10.1177/156482650903000305 19927604 | Country
39 | Imai CM, Gunnarsdottir I, Thorisdottir B, Halldorsson TI, Thorsdottir I. Associations between infant feeding practice prior to six months and body mass index at six years of age. Nutrients. 2014;6(4):1608–17. doi: 10.3390/nu6041608 24747694 | Intervention/exposure
40 | Johnson L, van Jaarsveld CHM, Llewellyn CH, Cole TJ, Wardle J. Associations between infant feeding and the size, tempo and velocity of infant weight gain: SITAR analysis of the Gemini twin birth cohort. Int J Obes. 2014;38(7):980–7. doi: 10.1038/ijo.2014.61 | Study design
41 | Jonsdottir OH, Kleinman RE, Wells JC, Exclusive breastfeeding for 4 versus 6 months and growth in early childhood. Acta Paediatr. 2014;103(1):105–11. doi: 10.1111/apa.12433 24117808 | Intervention/exposure
42 | Jonsdottir OH, Thorsdottir I, Gunnlaugsson G, Fewtrell MS, Hibberd PL, Kleinman RE. Exclusive breastfeeding and developmental and behavioral status in early childhood. Nutrients. 2013;5(11):4414–28. doi: 10.3390/nu5114414 24284608 | Intervention/exposure
43 | Jonsdottir OH, Thorsdottir I, Hibberd PL, Timing of the introduction of complementary foods in infancy: a randomized controlled trial. Pediatrics. 2012;130(6):1038–45. doi: 10.1542/peds.2011-3838 23147979 | Intervention/exposure
44 | Kalies H, Heinrich J, Borte N, The effect of breastfeeding on weight gain in infants: results of a birth cohort study. Eur J Med Res. 2005;10(1):36–42.15737952 | Intervention/exposure
45 | Khadivzadeh T, Parsai S. Effect of exclusive breastfeeding and complementary feeding on infant growth and morbidity. East Mediterr Health J. 2004;10(3):289–94.16212203 | Country
46 | Kramer MS, Barr RG, Leduc DG, Boisjoly C, McVey-White L, Pless IB. Determinants of weight and adiposity in the first year of life. J Pediatr. 1985;106(1):10–4. doi: 10.1016/s0022-3476(85)80456-x 3965671 | Intervention/exposure
47 | Kramer MS, Barr RG, Leduc DG, Boisjoly C, Pless IB. Infant determinants of childhood weight and adiposity. J Pediatr. 1985;107(1):104–7. doi: 10.1016/s0022-3476(85)80627-2 4009326 | Intervention/exposure
48 | Kramer MS, Guo T, Platt RW, Feeding effects on growth during infancy. J Pediatr. 2004;145(5):600–5. doi: 10.1016/j.jpeds.2004.06.069 15520757 | Country
49 | Lauver MA, Hizon L, Bulla A, Connell C, Wagoner B. Infant feeding practices: the effect on six month weight. J Kans Med Soc. 1981;82(9):403–6.7288260 | Intervention/exposure
50 | Layte R, Bennett A, McCrory C, Kearney J. Social class variation in the predictors of rapid growth in infancy and obesity at age 3 years. Int J Obes. 2014;38(1):82–90. doi: 10.1038/ijo.2013.160 | Intervention/exposure
51 | Leary SD, Lawlor DA, Davey Smith G, Brion MJ, Ness AR. Behavioural early-life exposures and body composition at age 15 years. Nutr Diabetes. 2015;5:e150. doi: 10.1038/nutd.2014.47 25664839 | Intervention/exposure
52 | Libuda L, Mesch CM, Stimming M, Fatty acid supply with complementary foods and LC-PUFA status in healthy infants: results of a randomised controlled trial. Eur J Nutr. 2016;55:1633–44. doi: 10.1007/s00394-015-0982-2 26169870 | Directness of experimental studies
53 | Lind T, Persson L, Lonnerdal B, Stenlund H, Hernell O. Effects of weaning cereals with different phytate content on growth, development and morbidity: a randomized intervention trial in infants from 6 to 12 months of age. Acta Pediatr. 2004;93(12):1575–82. doi: 10.1080/08035250410018355 | Directness of experimental studies
54 | Liu DS, Bates CJ, Yin TA, Wang XB, Lu CQ. Nutritional efficacy of a fortified weaning rusk in a rural area near Beijing. Am J Clin Nutr. 1993;57(4):506–11. doi: 10.1093/ajcn/57.4.506 8460605 | Country
55 | Lonnerdal B, Chen CL. Effects of formula protein level and ratio on infant growth, plasma amino acids and serum trace elements. II. Follow-up formula. Acta Paediatr Scand. 1990;79(3):266–73. doi: 10.1111/j.1651-2227.1990.tb11455.x 2333740 | Country
56 | Makela J, Vaarno J, Kaljonen A, Niinikoski H, Lagstrom H. Maternal overweight impacts infant feeding patterns--the STEPS Study. Eur J Clin Nutr. 2014;68:43–9. doi: 10.1038/ejcn.2013.229 24219892 | Intervention/exposure
57 | Makrides M, Hawkes JS, Neumann MA, Gibson RA. Nutritional effect of including egg yolk in the weaning diet of breast-fed and formula-fed infants: a randomized controlled trial. Am J Clin Nutr. 2002;75(6):1084–92. doi: 10.1093/ajcn/75.6.1084 12036817 | Directness of experimental studies
58 | Makrides M, Leeson R, Gibson RA, Simmer K. A randomized controlled clinical trial of increased dietary iron in breast-fed infants. J Pediatr. 1998;133(4):559–62. doi: 10.1016/s0022-3476(98)70069-1 9787699 | Intervention/exposure
59 | Moss BG, Yeaton WH. Early childhood healthy and obese weight status: potentially protective benefits of breastfeeding and delaying solid foods. Matern Child Health J. 2014;18(5):1224–32. doi: 10.1007/s10995-013-1357-z 24057991 | Intervention/exposure
60 | Neutzling MB, Hallal PRC, Araujo CLP, Infant feeding and obesity at 11 years: prospective birth cohort study. Int J Pediatr Obes. 2009;4(3):143–9. doi: 10.1080/17477160802453530 19353369 | Country
61 | Olaya GA, Lawson M, Fewtrell MS. Efficacy and safety of new complementary feeding guidelines with an emphasis on red meat consumption: a randomized trial in Bogota, Colombia. Am J Clin Nutr. 2013;98(4):983–93. doi: 10.3945/ajcn.112.053595 23945724 | Intervention/exposure
62 | Piwoz EG, Creed de Kanashiro H, Lopez de Romana GL, Black RE, Brown KH. Feeding practices and growth among low-income Peruvian infants: a comparison of internationally-recommended definitions. Int J Epidemiol. 1996;25(1):103–14. doi: 10.1093/ije/25.1.103 8666477 | Country
63 | Quandt SA. The effect of beikost on the diet of breast-fed infants. J Am Diet Assoc. 1984;84(1):47–51 6690564 | Intervention/exposure
64 | Reilly JJ, Armstrong J, Dorosty AR, Early life risk factors for obesity in childhood: cohort study. BMJ. 2005;330(7504):1357. doi: 10.1136/bmj.38470.670903.E0 15908441 | Intervention/exposure
65 | Robinson SM, Marriott LD, Crozier SR, Variations in infant feeding practice are associated with body composition in childhood: a prospective cohort study. J Clin Endocrinol Metab. 2009;94:2799–805. doi: 10.1210/jc.2009-0030 | Intervention/exposure
66 | Rose CM, Savage JS, Birch LL. Patterns of early dietary exposures have implications for maternal and child weight outcomes. Obesity. 2016;24(2):430–8. doi: 10.1002/oby.21349 26717908 | Intervention/exposure
67 | Salmenpera L, Perheentupa J, Siimes MA. Exclusively breast-fed healthy infants grow slower than reference infants. Pediatr Res. 1985;19(3):307–12. doi: 10.1203/00006450-198503000-00011 3982892 | Intervention/exposure
68 | Schwartz J, Dube K, Sichert-Hellert W, Modification of dietary polyunsaturated fatty acids via complementary food enhances n-3 long-chain polyunsaturated fatty acid synthesis in healthy infants: a double blinded randomised controlled trial. Arch Dis Child. 2009;94(11):876–82. doi: 10.1136/adc.2008.146027 19193660 | Directness of experimental studies
69 | Seach KA, Dharmage SC, Lowe AJ, Dixon JB. Delayed introduction of solid feeding reduces child overweight and obesity at 10 years. Int J Obes. 2010;34(10):1475–9. doi: 10.1038/ijo.2010.101 | Intervention/exposure
70 | Tang M, Krebs NF. High protein intake from meat as complementary food increases growth but not adiposity in breastfed infants: a randomized trial. Am J Clin Nutr. 2014;100(5):1322–8. doi: 10.3945/ajcn.114.088807 25332329 | Directness of experimental studies
71 | Tantracheewathorn S. Growth of breast-fed and formula-fed infants compared with national growth references of Thai children. J Med Assoc Thai. 2005;88(2):168–75.15962666 | Intervention/exposure; Country
72 | van Rossem L, Kiefte-de Jong JC, Looman CW, Weight change before and after the introduction of solids: results from a longitudinal birth cohort. Br J Nutr. 2013;109:370–5. doi: 10.1017/S0007114512001055 22475475 | Intervention/exposure
73 | Victora CG, Morris SS, Barros FC, Horta BL, Weiderpass E, Tomasi E. Breast-feeding and growth in Brazilian infants. Am J Clin Nutr. 1998;67(3):452–8. doi: 10.1093/ajcn/67.3.452 9497189 | Country
74 | Villalpando S, Lopez-Alarcon M. Growth faltering is prevented by breast-feeding in underprivileged infants from Mexico City. J Nutr. 2000;130(3):546–52. doi: 10.1093/jn/130.3.546 10702583 | Country
75 | Virtanen MA, Svahn CJ, Viinikka LU, Raiha NC, Siimes MA, Axelsson IE. Iron-fortified and unfortified cow's milk: effects on iron intakes and iron status in young children. Acta Paediatr. 2001;90(7):724–31.11519973 | Intervention/exposure
76 | Walter T, Dallman PR, Pizarro F, Effectiveness of iron-fortified infant cereal in prevention of iron deficiency anemia. Pediatrics. 1993;91(5):976–82.8474819 | Comparator
77 | Warrington S, Storey DM. Comparative studies on Asian and Caucasian children. 2: Nutrition, feeding practices and health. Eur J Clin Nutr. 1988;42(1):69–79.3371300 | Intervention/exposure
78 | Wells JC, Jonsdottir OH, Hibberd PL, Randomized controlled trial of 4 compared with 6 mo of exclusive breastfeeding in Iceland: differences in breast-milk intake by stable-isotope probe. Am J Clin Nutr. 2012;96(1):73–9. doi: 10.3945/ajcn.111.030403 22592102 | Intervention/exposure
79 | Wells JC, Stanley M, Laidlaw AS, Day JM, Davies PS. Energy intake in early infancy and childhood fatness. Int J Obes Relat Metab Disord. 1998;22(5):387–92. doi: 10.1038/sj.ijo.0800572 9622334 | Intervention/exposure
80 | Wen LM, Baur LA, Rissel C, Xu H, Simpson JM. Correlates of body mass index and overweight and obesity of children aged 2 years: findings from the healthy beginnings trial. Obesity. 2014;22(7):1723–30. doi: 10.1002/oby.20700 24415528 | Intervention/exposure
81 | Wen X, Kong KL, Eiden RD, Sharm NN, Xie C. Sociodemographic differences and infant dietary patterns. Pediatrics. 2014;134(5):e1387–98. doi: 10.1542/peds.2014-1045 25311608 | Intervention/exposure
82 | Wilson AC, Forsyth JS, Greene SA, Irvine L, Hau C, Howie PW. Relation of infant diet to childhood health: seven year follow up of cohort of children in Dundee infant feeding study. BMJ. 1998;316(7124):21–5. doi: 10.1136/bmj.316.7124.21 9451261 | Intervention/exposure
83 | Wolman PG. Feeding practices in infancy and prevalence of obesity in preschool children. J Am Diet Assoc. 1984;84(4):436–8.6707400 | Intervention/exposure
84 | World Health Organization. Growth of healthy infants and the timing, type, and frequency of complementary foods. Am J Clin Nutr. 2002;76(3):620–7. doi: 10.1093/ajcn/76.3.620 | Intervention/exposure
85 | Worobey J, Lopez MI, Hoffman DJ. Maternal behavior and infant weight gain in the first year. J Nutr Educ Behav. 2009;41(3):169–75. doi: 10.1016/j.jneb.2008.06.005 19411050 | Intervention/exposure
86 | Worobey J, Pena J, Ramos I, Espinosa C. Infant difficulty and early weight gain: does fussing promote overfeeding? Matern Child Nutr. 2014;10:295–303. doi: 10.1111/j.1740-8709.2012.00410.x 22591002 | Intervention/exposure
87 | Yeung DL, Pennell MD, Leung M, Hall J. Infant fatness and feeding practices: a longitudinal assessment. J Am Diet Assoc. 1981;79(5):531–5.7288058 | Intervention/exposure
88 | Yeung GS, Zlotkin SH. Efficacy of meat and iron-fortified commercial cereal to prevent iron depletion in cow milk-fed infants 6 to 12 months of age: a randomized controlled trial. Can J Public Health. 2000;91(4):263–7. doi: 10.1007/BF03404285 10986782 | Directness of experimental studies; Intervention/exposure
89 | Zheng JS, Liu H, Zhao YM, Complementary feeding and childhood adiposity in preschool-aged children in a large Chinese cohort. J Pediatr. 2015;166(2):326–31.e2. doi: 10.1016/j.jpeds.2014.11.010 25491091 | Country
90 | Zhou L, He G, Zhang J, Risk factors of obesity in preschool children in an urban area in China. Eur J Pediatr. 2011;170(11):1401–6. doi: 10.1007/s00431-011-1416-7 21365176 | Country

The following table (Table A 13) lists the articles excluded after full-text screening for the updated systematic review question. At least 1 reason for exclusion is provided for each article, though this may not reflect all possible reasons. Information about articles excluded after title and abstract screening is available upon request.

Table A 13 Articles excluded after full-text screening

| Citation | Rationale
1 | Adams ED, Lipman TH. The Impact of Timing of Introduction of Solids on Infant Body Mass Index. MCN Am J Matern Child Nurs. 2017. 42(3):186–186. | Study design
2 | Aldana-Parra F, Vega GO, Fewtrell M. Associations between maternal BMI, breastfeeding practices and infant anthropometric status in Colombia; secondary analysis of ENSIN 2010. BMC Public Health. 2020. 20(1):232.32059659 | Study design
3 | Alderete, E, Bejarano, I, Rodríguez, A. Beverage intake and obesity in early childhood: evidence form primary health care clients in Northwest Argentina. J Dev Orig Health Dis. 2016. 7(3):244–252.26639571 | Age at intervention/exposure
4 | Anderson CE, Whaley SE, Crespi CM, Wang MC, Chaparro MP. Every month matters: longitudinal associations between exclusive breastfeeding duration, child growth and obesity among WIC-participating children. J Epidemiol Community Health. 2020. 74(10):785–791.32611693 | Intervention/exposure
5 | Anderson CE, Whaley SE, Crespi CM, Wang MC, Chaparro MP. Mixed Infant Feeding Is Not Associated With Increased Risk of Decelerated Growth Among WIC-Participating Children in Southern California. 2021. 8:723501.34778333 | Intervention/exposure
6 | Appak YC, Aksoy B, Tinaztepe T, Evaluation of the frequency of obesity and associated factors in children of obese and overweight mothers. Journal of Pediatric Research. 2019. 6(3):228–233. | Study design
7 | Ardıç C, Omar E. Obesity frequency and related risk factors in primary school children. European Research Journal. 2019. 5(3):467–472. | Study design
8 | Ardic C, Usta O, Omar E, Yildiz C, Memis E. Effects of infant feeding practices and maternal characteristics on early childhood obesity. Arch Argent Pediatr. 2019. 117(1):26–33.30652443 | Intervention/exposure
9 | Aris IM, Bernard JY, Chen LW, Modifiable risk factors in the first 1000 days for subsequent risk of childhood overweight in an Asian cohort: significance of parental overweight status. Int J Obes (Lond). 2018. 42(1):44–51. | Intervention/exposure
10 | Aris IM, Soh SE, Tint MT, Associations of infant milk feed type on early postnatal growth of offspring exposed and unexposed to gestational diabetes in utero. Eur J Nutr. 2017. 56(1):55–64.26415764 | Intervention/exposure
11 | Arredondo A, Lugo OBR, Orozco E, de la Rosa CPT. Breastfeeding and feeding practices in the first year of life and its association with overweight and obesity of children in Mexico. Rev Bras Saude Mater Infant. 2021. 21(4):1109. doi:10.1590/1806-93042021000400009. | Study design
12 | Ashman AM, Collins CE, Weatherall L, A cohort of Indigenous Australian women and their children through pregnancy and beyond: the Gomeroi gaaynggal study. J Dev Orig Health Dis. 2016. 7(4):357–68.27080434 | Intervention/exposure, Outcome
13 | Ashman AM, Collins CE, Weatherall LJ, Dietary intakes and anthropometric measures of Indigenous Australian women and their infants in the Gomeroi gaaynggal cohort. J Dev Orig Health Dis. 2016. 7(5):481–497.27345431 | Study design
14 | Atkin LM, Davies PS. Diet composition and body composition in preschool children. Am J Clin Nutr 2000. 72(1):15–21.10871555 | Age at intervention/exposure
15 | Atkins LA, McNaughton SA, Campbell KJ, Szymlek-Gay EA. Iron intakes of Australian infants and toddlers: findings from the Melbourne Infant Feeding, Activity and Nutrition Trial (InFANT) Program Br J Nutr. 2016. 115(2):285‐293. | Outcome
16 | Augusto ÉO, Bonucci VG, Cardoso RV, Morais MB. Complementary feeding and nutritional status infants on cow's milk proteins elimination diet. Rev Paul Pediatr. 2022. 40:e20200429.35648982 | Study design, Intervention/exposure, Outcome
17 | Azad MB, Vehling L, Chan D, Infant Feeding and Weight Gain: Separating Breast Milk From Breastfeeding and Formula From Food. Pediatrics. 2018. 142(4):e20181092.30249624 | Intervention/exposure
18 | Azad MB. Infant Feeding and the Developmental Origins of Chronic Disease in the CHILD Cohort: Role of Human Milk Bioactives and Gut Microbiota. Breastfeeding Medicine. 2019. 14(S1):S22–S24.30985197 | Study design
19 | Bably MB, Paul R, Laditka SB, Racine EF. Factors Associated with the Initiation of Added Sugar among Low-Income Young Children Participating in the Special Supplemental Nutrition Program for Women, Infants, and Children in the US. Nutrients. 2021. 13(11):3888.34836143 | Outcome
20 | Bably MB, Laditka SB, Paul R, Racine EF. Age of Bottle Cessation and BMI-for-Age Percentile among Children Aged Thirty-Six Months Participating in WIC. Child Obes. 2022. 18(3):197–205. doi:10.1089/chi.2021.0119.34551266 | Intervention/exposure
21 | Baran J, Weres A, Czenczek-Lewandowska E, Early Eating Patterns and Overweight and Obesity in a Sample of Preschool Children in South-East Poland. Int J Environ Res Public Health. 2019. 16(17):3064.31450738 | Study design, Age at intervention/exposure
22 | Barbosa C, Costa A, Hetherington MM, Oliveira A. Association of early feeding practices with dietar patterns of 7-year-olds from the birth cohort Generation XXI. Appetite. 2022. 171:105909.34986399 | Outcome
23 | Barrera CM, Perrine CG, Li R, Scanlon KS. Age at Introduction to Solid Foods and Child Obesity at Years. Child Obes. 2016. 12(3):188–192.27058343 | Duplicate data
24 | Barrett, KJ, Thompson, AL. Infant eating behaviors and Milk feeding independently predict infant size. Am J Hum Biol. 2022. 34(4):e23678. doi:10.1002/ajhb.23678.34506053 | Intervention/exposure
25 | Barros VO, Amorim MR, Melo AO, Tavares JS, Silva AC, Alves JG. Abdominal Fat Distribution among Breastfed and Formula-Fed Infants. Breastfeeding Medicine. 2016. 11(5):231–234.27104359 | Intervention/exposure
26 | Barroso M, Beth SA, Voortman T, Dietary Patterns After the Weaning and Lactation Period A Associated With Celiac Disease Autoimmunity in Children. Gastroenterology. 2018. 154(8):2087–2096 e7.29481779 | Outcome
27 | Beck AL, Fernandez A, Rojina J, Cabana M. Randomized Controlled Trial of a Clinic-Based Intervention to Promote Healthy Beverage Consumption Among Latino Children. Clin Pediatr (Phila) 2017. 56(9):838–844.28553726 | Age at intervention/exposure
28 | Beleza LO, Ribeiro LM, Paula RAP, Guarda L, Vieira GB, Costa KSF. Profile of at-risk newborns attended by nurses in outpatient follow-up clinic: a retrospective cohort study. Rev Lat Am Enfermagem. 2019. 27:e3113.30698216 | Intervention/exposure
29 | Bell KA, Wagner CL, Feldman HA, Shypailo RJ, Belfort MB. Associations of infant feeding with trajectories of body composition and growth. Am J Clin Nutr. 2017. 106(2):491–498.28659299 | Intervention/exposure
30 | Bell LK, Schammer C, Devenish G, Dietary patterns and risk of obesity and early childhood caries in Australian toddlers: Findings from an australian cohort study. Nutrients. 2019. 11(11):282 30696021 | Intervention/exposure
31 | Bell S, Yew SSY, Devenish G, Ha D, Do L, Scott J. Duration of Breastfeeding, but Not Timing of Solid Food, Reduces the Risk of Overweight and Obesity in Children Aged 24 to 36 Months: Findings from an Australian Cohort Study. Int J Environ Res Public Health. 2018. 15(4):599.29587447 | Intervention/exposure
32 | Bel-Serrat S, Mouratidou T, Börnhorst C, Food consumption and cardiovascular risk factors i European children: the IDEFICS study. Pediatr Obes. 2013. 8(3):225–236.23225768 | Age at intervention/exposure
33 | Bentil HJ, Steiner-Asiedu M, Lartey A. Comparison of the complementary feeding practices betwe mothers with twins and mothers with singletons. Pan Afr Med J. 2016. 24:52.27642393 | Country
34 | Berkey CS, Gardner JD, Frazier AL, Colditz GA. Relation of childhood diet and body size to menarche and adolescent growth in girls. Am J Epidemiol. 2000. 152(5):446–52.10981459 | Intervention/exposure
35 | Bernabe E, Ballantyne H, Longbottom C, Pitts NB. Early Introduction of Sugar-Sweetened Beverages and Caries Trajectories from Age 12 to 48 Months. J Dent Res. 2020. 99(8):898–906.32374714 | Outcome
36 | Besharat Pour M, Bergström A, Bottai M, Magnusson J, Kull I, Moradi T. Age at adiposity rebound and body mass index trajectory from early childhood to adolescence; differences by breastfeeding and maternal immigration background. Pediatr Obes. 2017. 12(1):75–84. | Intervention/exposure
37 | Betoko A, Lioret S, Heude B, Influence of infant feeding patterns over the first year of life on growth from birth to 5 years. Pediatr Obes. 2017. 12 Suppl 1:94–101.28299906 | Intervention/exposure
38 | Beyerlein A, Uusitalo UM, Virtanen SM, Intake of Energy and Protein is Associated with Overweight Risk at Age 5.5 Years: Results from the Prospective TEDDY Study. Obesity. 2017. 25(8): 1435–1441.28650578 | Intervention/exposure
39 | Bhargava A. Protein and micronutrient intakes are associated with child growth and morbidity from infancy to adulthood in the Philippines. J Nutr. 2016. 146(1): 133–141.26661837 | Country
40 | Black MM, Hager ER, Wang Y, Toddler obesity prevention: A two-generation randomized attention-controlled trial. Matern Child Nutr. 2021. 17(1):e13075.32885909 | Intervention/exposure
41 | Bloomfield FH, Agostoni C. The potential impact of feeding formula-fed infants according to published recommendations. Pediatr Res. 2020. 88(4):526–528.32634816 | Study design
42 | Bong MW, Karim NA, Noor IM. Nutritional status and complementary feeding among Penan infants and young children in rural Sarawak, Malaysia. Malays J Nutr. 2018. 24(4):539–550. | Study design
43 | Boulton TJ, Magarey AM. Effects of differences in dietary fat on growth, energy and nutrient intake from infancy to eight years of age. Acta Paediatr. 1995. 84(2):146–50.7756798 | Intervention/exposure
44 | Bournez M, Ksiazek E, Wagner S, Factors associated with the introduction of complementary feeding in the French ELFE cohort study. Matern Child Nutr. 2018. 14(2):e12536.29052955 | Outcome
45 | Brambilla P, Bedogni G, Pietrobelli A, Cianfarani S, Agostoni C. Predictors of blood pressure at 7-13 years: The "new millennium baby" study. Nutr Metab Cardiovasc Dis. 2016. 26(8):706–12.27048714 | Intervention/exposure
46 | Braun KV, Erler NS, Kiefte-de Jong JC, Dietary intake of protein in early childhood is associated with growth trajectories between 1 and 9 years of age. J Nutr. 2016. 146(11 ):2361 –2367.27733529 | Intervention/exposure
47 | Breastmilk Lipid May Affect Early Childhood Obesity. Today's Dietitian. 2021.23(2):58–58. | Study design, Intervention/exposure, Publication status
48 | Breij LM, Abrahamse-Berkeveld M, Acton D, De Lucia Rolfe E, Ong KK, Hokken-Koelega ACS. Impact of Early Infant Growth, Duration of Breastfeeding and Maternal Factors on Total Body Fat Mass and Visceral Fat at 3 and 6 Months of Age. Ann Nutr Metab. 2017. 71(3-4):203–210.29136614 | Intervention/exposure
49 | Breij LM, Mulder MT, van Vark-van der Zee LC, Hokken-Koelega ACS. Appetite-regulating hormones in early life and relationships with type of feeding and body composition in healthy term infants. Eur J Nutr. 2017. 56(4):1725–1732.27170102 | Intervention/exposure
50 | Brito A, Olivares M, Pizarro T, Rodriguez L, Hertrampf E. Chilean Complementary Feeding Program reduces anemia and improves iron status in children aged 11 to 18 months. Food Nutr Bull. 2013. 34(4):378–385.24605687 | Study design
51 | Brugailleres P, Issanchou S, Nicklaus S, Chabanet C, Schwartz C. Caloric compensation in infants: developmental changes around the age of 1 year and associations with anthropometric measurements up to 2 years. Am J Clin Nutr. 2019. 109(5):1344–1352.30997507 | Intervention/exposure
52 | Budree S, Goddard E, Brittain K, Cader S, Myer L, Zar HJ. Infant feeding practices in a South African birth cohort-A longitudinal study. Matern Child Nutr. 2017. 13(3):e12371.27696743 | Country
53 | Buyuk Yaytokgil /1=S;/, G/1=u''/venir H, /1=C;/uhaci /1=C;/akir B, The Effect of an Elimination Diet on Early Childhood Growth in Children with Egg and/or Cow’s Milk Allergies. Asthma Allergy Immunology. 2022. 20(1 ):16–24. | Study design
54 | Byrne R, Yeo MEJ, Malian K, Magarey A, Daniels L. Is higher formula intake and limited dietary diversity in Australian children at 14 months of age associated with dietary quality at 24 months?. Appetite. 2018. 120:240–245.28899651 | Outcome
55 | Byrne R, Zhou Y, Perry R, Mauch C, Magarey A. Beverage intake of Australian children and relationship with intake of fruit, vegetables, milk and body weight at 2, 3.7 and 5 years of age. Nutr Diet. 2018. 75(2): 159–166.29424057 | Age at intervention/exposure
56 | Camier A, Ciss/1=e'/ AH, Lioret S, Infant feeding practices associated with adiposity peak and rebound in the EDEN mother-child cohort. Int J Obes. 2022. 46(4):809–16. | Intervention/exposure
57 | Campbell KJ, Lioret S, McNaughton SA, A parent-focused intervention to reduce infant obesity risk behaviors: a randomized trial. Pediatrics. 2013. 131(4):652–660.23460688 | Intervention/exposure
58 | Cantoral A, T/1=e'/llez-Rojo MM, Ettinger AS, Hu H, Hern/1=a'/ndez-/1=A'/vila M, Peterson K. Early introduction and cumulative consumption of sugar-sweetened beverages during the pre-school period and risk of obesity at 8-14 years of age. Pediatr Obes. 2016. 11(1 ):68–74.25891908 | Duplicate data
59 | Caroli M, Vania A, Tomaselli MA, Breastfed and formula-fed infants: Need of a different complementary feeding model?. Nutrients. 2021. 13(11 ):3756. doi:10.3390/nu13113756.34836012 | Outcome
60 | Carrut BR, Skinner JD. The role of dietary calcium and other nutrients in moderating body fat in preschool children. Int J Obes. 2001. 25(4):559–566. | Age at intervention/exposure
61 | Cassimos D, Sidiropoulos H, Batzios S, Balodima V, Christoforidis A. Sociodemographic and dietary risk factors for excess weight in a greek pediatric population living in Kavala, Northern Greece. Nutrition in Clinical Practice. 2011. 26(2):186–191.21447773 | Study design
62 | Castro TG, Gerritsen S, Teixeira JA, An index measuring adherence to New Zealand Infant Feeding Guidelines has convergent validity with maternal socio-demographic and health behaviours and with children's body size. Br J Nutr. 2022. 127(7):1073–85.34212833 | Intervention/exposure
63 | Cervo MMC, Mendoza DS, Barrios EB, Panlasigui LN. Effects of Nutrient-Fortified Milk-Based Formula on the Nutritional Status and Psychomotor Skills of Preschool Children. J Nutr Metab. 2017. 2017:6456738.29075529 | Age at intervention/exposure
64 | Chai LK, Collins CE, May C, Brown LJ, Ashman A, Burrows TL. Fidelity and acceptability of a family-focused technology-based telehealth nutrition intervention for child weight management. J Telemed Telecare. 2021. 27(2):98–109.31390947 | Intervention/exposure, Age at intervention/exposure
65 | Chang JY, Park JS, Shin S, Yang HR, Moon JS, Ko JS. Mercury exposure in healthy Korean weaning-age infants: Association with growth, feeding and fish intake. Int J Environ Res Public Health. 2015. 12(11):14669. doi:10.3390/ijerph121114669.26593931 | Study design, Outcome
66 | Chaparro MP, Anderson CE, Crespi CM, Wang MC, Whaley SE. The new child food package is associated with reduced obesity risk among formula fed infants participating in the Special Supplemental Nutrition Program for Women, Infants and Children (WIC) in Los Angeles County, California, 2003-2016. Int J Behav Nutr Phys Act. 2020. 17(1):18.32041634 | Intervention/exposure
67 | Chaparro MP, Wang MC, Anderson CE, Crespi CM, Whaley SE. The Association between the 2009 WIC Food Package Change and Early Childhood Obesity Risk Varies by Type of Infant Package Received. J Acad Nutr Diet. 2020. 120(3):371–385.31831385 | Intervention/exposure
68 | Chen Y, Han L, Su W, Breastfeeding on childhood obesity in children were large-for-gestational age: retrospective study from birth to 4 years. Sci Rep. 2022. 12(1):4226. doi:10.1038/s41598-022-08275-0.35273323 | Intervention/exposure
69 | Cheng TS, Loy SL, Toh JY, Predominantly nighttime feeding and weight outcomes in infants. Am J Clin Nutr. 2016. 104(2):380–8.27385614 | Intervention/exposure
70 | Cheng Z, Shi L, Li Y, Wang Y, Zhang J. Using structural equation modelling to assess factors influencing children's growth and nutrition in rural China. Public Health Nutr. 2018. 21(6):1167–1175.29224576 | Intervention/exposure
71 | Chiang KV, Hamner HC, Li R, Perrine CG. Timing of Introduction of Complementary Foods - United States, 2016-2018. MMWR Morb Mortal Wkly Rep. 2020. 69(47):1787–1791.33237894 | Study design
72 | Chiasson MA, Scheinmann R, Hartel D, Predictors of Obesity in a Cohort of Children Enrolled in WIC as Infants and Retained to 3 Years of Age. J Community Health. 2016. 41(1):127–133.26280211 | Study design, Intervention/exposure
73 | Chung A, Peeters A, Gearon E, Backholer K. Contribution of discretionary food and drink consumption to socio-economic inequalities in children’s weight: Prospective study of Australian children. Int J Epidemiol. 2018. 47(3):820–828.29514246 | Age at intervention/exposure
74 | Cloutier MM, Wiley JF, Kuo CL, Cornelius T, Wang Z, Gorin AA. Outcomes of an early childhood obesity prevention program in a low-income community: a pilot, randomized trial. Pediatr Obes. 2018. 13(11):677–685.30156058 | Intervention/exposure
75 | Cont G, Paviotti G, Montico M, TAS2R38 bitter taste genotype is associated with complementary feeding behavior in infants. Genes Nutr. 2019. 14:13.31073343 | Intervention/exposure, Outcome
76 | Costa CS, Campagnolo PD, Lumey LH, Vitolo MR. Effect of maternal dietary counselling during the 1st year of life on glucose profile and insulin resistance at the age of 8 years: a randomised field trial. Br J Nutr. 2017. 117(1):134–141.28098052 | Country
77 | Coxon C, Devenish G, Ha D, Do L, Scott JA. Sources and Determinants of Discretionary Food Intake in a Cohort of Australian Children Aged 12-14 Months. Int J Environ Res Public Health. 2019. 17(1):80.31861905 | Study design, Outcome
78 | Cummings JR, Faith MS, Lipsky LM, Liu A, Mooney JT, Nansel TR. Prospective relations of maternal reward-related eating, pregnancy ultra-processed food intake and weight indicators, and feeding mode with infant appetitive traits. Int J Behav Nutr Phys Act. 2022. 19(1):100. doi:10.1186/s12966-022-01334-9.35922793 | Outcome
79 | Dagnelie PC, van Staveren WA, Vergote FJ, Nutritional status of infants aged 4 to 18 months on macrobiotic diets and matched omnivorous control infants: a population-based mixed-longitudinal study. II. Growth and psychomotor development. Eur J Clin Nutr. 1989. 43(5):325–38.2737170 | Intervention/exposure
80 | Dalrymple KV, Flynn AC, Seed PT, Modifiable early life exposures associated with adiposity and obesity in 3-year old children born to mothers with obesity. Pediatr Obes. 2021. 16(11):e12801.33998777 | Intervention/exposure, Age at intervention/exposure
81 | Damsgaard CT, Papadaki A, Jensen SM, Higher protein diets consumed ad libitum improve cardiovascular risk markers in children of overweight parents from eight European countries. J Nutr. 2013. 143(6):810–817.23596158 | Age at intervention/exposure
82 | Dang C, Hoyland L, Nanan R. Association of Early Introduction of Solids With Infant Sleep. JAMA Pediatr. 2019. 173:195. | Outcome
83 | Daniels L, Taylor RW, Williams SM, Impact of a modified version of baby-led weaning on iron intake and status: a randomised controlled trial. BMJ Open. 2018. 8(6):e019036. | Intervention/exposure, Outcome
84 | Daniels L, Taylor RW, Williams SM, Modified Version of Baby-Led Weaning Does Not Result in Lower Zinc Intake or Status in Infants: A Randomized Controlled Trial. J Acad Nutr Diet. 2018. 118(6):1006–1016 e1.29803269 | Outcome
85 | Davidsson L, Mackenzie J, Kastenmayer P, Dietary fiber in weaning cereals: A study of the effect on stool characteristics and absorption of energy, nitrogen, and minerals in healthy infants. J Pediatr Gastroenterol Nutr. 1996. 22(2):167–179.8642490 | Intervention/exposure
86 | Davis KE, Klingenberg A, Massey-Stokes M, The Baby Bites Text Messaging Project with randomized controlled trial: texting to improve infant feeding practices. mHealth. 2023. 9:11. doi:10.21037/MHEALTH-22-31.37089270 | Intervention/exposure
87 | de Beer M, Vrijkotte TG, Fall CH, van Eijsden M, Osmond C, Gemke RJ. Associations of Infant Feeding and Timing of Weight Gain and Linear Growth during Early Life with Childhood Blood Pressure: Findings from a Prospective Population Based Cohort Study. PLoS One. 2016. 11(11):e0166281.27832113 | Outcome
88 | de Beer M, Vrijkotte TG, Fall CH, van Eijsden M, Osmond C, Gemke RJ. Correction: Associations of Infant Feeding and Timing of Weight Gain and Linear Growth during Early Life with Childhood Blood Pressure: Findings from a Prospective Population Based Cohort Study. PLoS One. 2016. 11(12):e0168920.27992607 | Outcome
89 | De Boer MD, Scharf RJ, Demmer RT. Sugar-sweetened beverages and weight gain in 2-to 5-year-old children. Pediatrics. 2013. 132(3):413–420.23918897 | Age at intervention/exposure
90 | de Faria DPB, Sillos MD, da Graça Leite Speridião P, de Morais MB. Outcome of food intake and nutritional status after discontinuation of a cow’s-milk-free diet post negative oral food challenge in infants and children. Allergol Immunopathol (Madr). 2022. 50(1):1. doi:10.15586/aei.v50i1.471. | Intervention/exposure, Age at intervention/exposure
91 | de Lima Lins AC, Pedraza DF. Growth rate of children of a cohort up to the sixth month of life. Velocidade de crescimento de crianças de uma coorte até o sexto mês de vida. 2021. 26(11):5777. doi:10.1590/1413-812320212611.22212020. | Language
92 | de Melo JMM, Dourado BLLFS, de Menezes RCE, Longo-Silva G, da Silveira JAC. Early onset of overweight among children from low-income families: The role of exclusive breastfeeding and maternal intake of ultra-processed food. Pediatr Obes. 2021. 16(12):e12825.34169658 | Intervention/exposure
93 | de Miranda Pereira TA, Gomes Freire AK, Santos Gonçalves VS. Exclusive breastfeeding and underweight in children under six months old monitored in primary health care in Brazil, 2017. 2021. Rev Paul Pediatr. 39:e2019293. doi:10.1590/1984-0462/2021/39/2019293. | Study design, Intervention/exposure
94 | De Rosso S, Schwartz C, Ducrot P, Nicklaus S. The Perceptions and Needs of French Parents and Pediatricians Concerning Information on Complementary Feeding. Nutrients. 2021. 13(7):2142.34206652 | Study design, Outcome
95 | de Silva-Sanigorski AM, Bell AC, Kremer P, Reducing obesity in early childhood: results from Romp & Chomp, an Australian community-wide intervention program. Am J Clin Nutr. 2010. 91(4):831–40.20147472 | Intervention/exposure
96 | de Vasconcellos MT. Body mass index: its relationship with food consumption and socioeconomic variables in Brazil. Eur J Clin Nutr. 1994. 48(Suppl 3):S115–23.7843148 | Country
97 | Deheeger M, Akrout M, Bellisle F, Rossignol C, Rolland-Cachera MF. Individual patterns of food intake development in children: a 10 months to 8 years of age follow-up study of nutrition and growth. Physiol Behav. 1996. 59(3):403–7.8700939 | Intervention/exposure
98 | Delisle Nystrom C, Cameron AJ, Campbell KJ, Hesketh KD. Variation in outcomes of the Melbourne Infant, Feeding, Activity and Nutrition Trial (INFANT) according to maternal education and age 2 and 3.5 years post-intervention. Public Health Nutr. 2021. 24(6):1460–1468.33427160 | Intervention/exposure
99 | Diana A, Haszard JJ, Irda Sari SY, RESEARCH ARTICLE Determination of modifiable risk factors for length-for-age z-scores among resource-poor Indonesian infants. PLoS One. 2021. 16(2):e0247247.33600460 | Country, Outcome
100 | Diana A, Mallard SR, Haszard JJ, Consumption of fortified infant foods reduces dietary diversity but has a positive effect on subsequent growth in infants from Sumedang district, Indonesia. PLoS One. 2017. 12(4):e0175952.28426828 | Country
101 | Differding MK, Doyon M, Bouchard L, Potential interaction between timing of infant complementary feeding and breastfeeding duration in determination of early childhood gut microbiota composition and BMI. Pediatr Obes. 2020. 15(8):e12642.32351036 | Intervention/exposure
102 | Do LG, Ha DH, Bell LK, Study of Mothers' and Infants' Life Events Affecting Oral Health (SMILE) birth cohort study: cohort profile. BMJ Open. 2020. 10(10):e041185. | Study design, Intervention/exposure
103 | Dodd JM, McPhee AJ, Deussen AR, Effects of an antenatal dietary intervention in overweight and obese women on 6 month infant outcomes: follow-up from the LIMIT randomised trial. Int J Obes (Lond). 2018. 42(7):1326–1335.29568100 | Intervention/exposure
104 | Dogan E, Yilmaz G, Caylan N, Turgut M, Gokcay G, Oguz MM. Baby-led complementary feeding: Randomized controlled study. Pediatr Int. 2018. 60(12):1073–1080.30074671 | Intervention/exposure
105 | Donkor HM, Grundt JH, Júlíusson PB, Social and somatic determinants of underweight, overweight and obesity at 5 years of age: A Norwegian regional cohort study. BMJ Open. 2017. 7(8):e014548. | Intervention/exposure, Age at intervention/exposure
106 | Dourado BLLFS, De Melo JMM, Longo-Silva G, de Menezes RCE, da Silveira JAC. Early-life determinants of excessive weight gain among low-income children: Examining the adherence of theoretical frameworks to empirical data using structural equation modelling. Pediatr Obes. 2022. 17(8):e12912. doi:10.1111/ijpo.12912. | Intervention/exposure
107 | Dugas C, Kearney M, Mercier R, Early life nutrition, glycemic and anthropometric profiles of children exposed to gestational diabetes mellitus in utero. Early Hum Dev. 2018. 118:37–41.29459222 | Intervention/exposure
108 | Dugas C, Perron J, Marc I, Weisnagel SJ, Robitaille J. Association between early introduction of fruit juice during infancy and childhood consumption of sweet-tasting foods and beverages among children exposed and unexposed to gestational diabetes mellitus in utero. Appetite. 2019. 132:190–195.30171916 | Study design, Outcome
109 | Durão C, Severo M, Oliveira A, Evaluating the effect of energy-dense foods consumption on preschool children’s body mass index: a prospective analysis from 2 to 4 years of age. Eur J Nutr. 2015. 54(5):835–843.25185968 | Age at intervention/exposure
110 | Eckhardt CL, Suchindran C, Gordon-Larsen P, Adair LS. The association between diet and height in the postinfancy period changes with age and socioeconomic status in Filipino youths. J Nutr. 2005. 135(9):2192–8.16140897 | Country
111 | El-Gamal FM, Babader R, Al-Shaikh M, Al-Harbi A, Al-Kaf J, Al-Kaf W. Study determinants of increased Z-Score of Body Mass Index in preschool-age children. BMC Res Notes. 2020. 13(1):186.32228683 | Study design
112 | Elliott LJ, Keown-Stoneman CDG, Birken CS, Jenkins DJA, Borkhoff CM, Maguire JL. Vegetarian Diet, Growth, and Nutrition in Early Childhood: A Longitudinal Cohort Study. Pediatrics. 2022. 149(6):e2021052598.35499383 | Intervention/exposure
113 | Emmett PM. Dietary Patterns during Complementary Feeding and Later Outcomes. Nestle Nutr Inst Workshop Ser. 2016. 85:145–154.27088342 | Study design
114 | Ercan N, Tel Adiguzel K. Effect of early childhood cow's milk elimination diet on eating behaviours, nutrition and growth status at age 2-6 years. J Hum Nutr Diet. 2022. 35(2):300–309.33974304 | Study design
115 | Eun Kyo H, Ju Hee K, Hey-Sung B, Association between complementary food introduction before age 4 months and body mass index at age 5-7 years: a retrospective population-based longitudinal cohort study. 2023. 36(3):787–97. | Intervention/exposure
116 | Faber M, Malan L, Kruger HS, Potential of Egg as Complementary Food to Improve Nutrient Intake and Dietary Diversity. Nutrients. 2022. 14(16):3396. doi:10.3390/nu14163396.36014905 | Outcome
117 | Fabiansen C, Phelan KPQ, Cichon B, Short Malnourished Children and Fat Accumulation With Food Supplementation. Pediatrics. 2018. 142(3):e20180679.30143567 | Country
118 | Fahmida U, Htet MK, Ferguson E, Effect of an Integrated Package of Nutrition Behavior Change Interventions on Infant and Young Child Feeding Practices and Child Growth from Birth to 18 Months: Cohort Evaluation of the Baduta Cluster Randomized Controlled Trial in East Java, Indonesia. Nutrients. 2020. 12(12):3851.33339415 | Country
119 | Faienza MF, Colaianni V, Di Ciaula A, Different Variation of Intra-familial Body Mass Index subjected to Covid-19 Lockdown. J Gastrointestin Liver Dis. 2022. 31(2):198–205.35574620 | Age at intervention/exposure
120 | Faith MS, Dennison BA, Edmunds LS, Stratton HH. Fruit juice intake predicts increased adiposity gain in children from low-income families: weight status-by-environment interaction. Pediatrics. 2006. 118(5):2066–75.17079580 | Age at intervention/exposure
121 | Fangupo LJ, Heath ALM, Williams SM, Impact of an early-life intervention on the nutrition behaviors of 2-y-old children: A randomized controlled trial1,2. Am J Clin Nutr. 2015. 102(3):704–712.26224299 | Intervention/exposure
122 | Feeney M, Du Toit G, Roberts G, et al. Impact of peanut consumption in the LEAP Study: Feasibility, growth, and nutrition. J Allergy Clin Immunol. 2016. 138(4):1108-1118. | Directness of experimental studies
123 | Feldman-Winter L, Burnham L, Grossman X, Matlak S, Chen N, Merewood A. Weight gain in the first week of life predicts overweight at 2 years: A prospective cohort study. Matern Child Nutr. 2018. 14(1):e12472.28636245 | Intervention/exposure
124 | Feng J, Gong Z, Wang Y, Huo J, Zhuo Q. Complementary Feeding and Malnutrition among Infants and Young Children Aged 6-23 Months in Rural Areas of China. Nutrients. 2022. 14(9):1807. doi:10.3390/nu14091807.35565773 | Study design
125 | Ferguson MC, O'Shea KJ, Hammer LD, The Impact of Following Solid Food Feeding Guides on BMI Among Infants: A Simulation Study. Am J Prev Med. 2019. 57(3):355–364.31353163 | Study design, Population
126 | Ferreira SS, Marchioni DML, Wall CR, Prevalence and maternal determinants of early and late introduction of complementary foods: Results from the Growing Up in New Zealand cohort study. Br J Nutr. 2023. 129(3):491–502.35403582 | Outcome
127 | Fitzgibbon ML, Stolley MR, Schiffer L, Van Horn L, KauferChristoffel K, Dyer A. Two-year follow-up results for Hip-Hop to Health Jr.: a randomized controlled trial for overweight prevention in preschool minority children. J Pediatr. 2005. 146(5):618–25.15870664 | Age at intervention/exposure
128 | Flaherman VJ, Cabana MD, McCulloch CE, Paul IM. Effect of Early Limited Formula on Breastfeeding Duration in the First Year of Life: A Randomized Clinical Trial. JAMA Pediatr. 2019. 173(8):729–735.31157878 | Intervention/exposure
129 | Fletcher S, Wright C, Jones A, Parkinson K, Adamson A. Tracking of toddler fruit and vegetable preferences to intake and adiposity later in childhood. Matern Child Nutr. 2017. 13(2):n/a-N.PAG. | Intervention/exposure, Outcome
130 | Flores-Barrantes P, Iguacel I, Iglesia-Altaba I, Moreno LA, Rodriguez G. Rapid Weight Gain, Infant Feeding Practices, and Subsequent Body Mass Index Trajectories: The CALINA Study. Nutrients. 2020. 12(10):3178.33080922 | Intervention/exposure
131 | Fogel A, McCrickerd K, Aris IM, Eating behaviors moderate the associations between risk factors in the first 1000 days and adiposity outcomes at 6 years of age. Am J Clin Nutr. 2020. 111(5):997–1006.32219418 | Intervention/exposure
132 | Fonseca PCA, Carvalho CA, Ribeiro SAV, Determinants of the mean growth rate of children under the age of six months: a cohort study. Cien Saude Colet. 2017. 22(8):2713–2726.28793085 | Study design
133 | Forbes JD, Azad MB, Vehling L, Association of Exposure to Formula in the Hospital and Subsequent Infant Feeding Practices With Gut Microbiota and Risk of Overweight in the First Year of Life. JAMA Pediatr. 2018. 172(7):e181161.29868719 | Intervention/exposure
134 | Freedman DS, Srinivasan SR, Cresanta JL, Webber LS, Berenson GS. Cardiovascular risk factors from birth to 7 years of age: the Bogalusa Heart Study. Serum lipids and lipoproteins. Pediatrics. 1987. 80(5 Pt 2):789–96.3478647 | Outcome
135 | Gaffney KF, Brito AV, Kitsantas P, Kermer DA. Early Feeding Practices and Weight Status at One Year of Age: A Comparison of Hispanic Immigrant Mother-Infant Dyads with Participants of the Infant Feeding Practices Study II. Child Obes. 2016. 12(5):384–91.27385467 | Duplicate data
136 | Geurtsen ML, Santos S, Gaillard R, Felix JF, Jaddoe VWV. Associations Between Intake of Sugar-Containing Beverages in Infancy With Liver Fat Accumulation at School Age. Hepatology. 2021. 73(2):560–570.33140427 | Outcome
137 | Ghodsi D, Omidvar N, Rashidian A, Eini-Zinab H, Raghfar H, Aghayan M. Effectiveness of the national food supplementary program on children growth and nutritional status in Iran. Matern Child Nutr. 2018. 14(3):e12591.29573559 | Intervention/exposure
138 | Gibson LA, Hernandez Alava M, Kelly MP, Campbell MJ. The effects of breastfeeding on childhood BMI: a propensity score matching approach. J Public Health (Oxf). 2017. 39(4):e152–e160.27613768 | Intervention/exposure
139 | Giorgini E, Fisberg M, De Paula RA, Ferreira AM, Valle J, Braga JA. The use of sweet rolls fortified with iron bis-glycinate chelate in the prevention of iron deficiency anemia in preschool children. Arch Latinoam Nutr. 2001. 51(1 Suppl 1):48–53.11688082 | Country
140 | Giovannini M, Riva E, Banderali G, Feeding practices of infants through the first year of life in Italy. Acta Paediatrica, International Journal of Paediatrics. 2004. 93(4):492–497. | Outcome
141 | Gishti O, Gaillard R, Durmuş B, Infant diet and metabolic outcomes in school-age children. the Generation R Study. Eur J Clin Nutr. 2014. 68(9):1008–1015.24781689 | Outcome
142 | Goetz AR, Mara CA, Stark LJ. Greater Breastfeeding in Early Infancy Is Associated with Slower Weight Gain among High Birth Weight Infants. J Pediatr. 2018. 201:27–33 e4.30007772 | Intervention/exposure
143 | Goetz AR, Rybak TM, Peugh JL, Stark LJ. Early-life determinants of excess weight in children born heavy. Pediatr Obes. 2020. 15(2):e12580.31689003 | Intervention/exposure
144 | Golding J, Iles-Caven Y, Ellis G, Gregory S, Nowicki S. The relationship between parental locus of control and adolescent obesity: a longitudinal pre-birth cohort. Int J Obes (Lond). 2019. 43(4):724–734.29983415 | Intervention/exposure
145 | Golova N, Eskander J, Pho A, Preventing the Early Introduction of Juice and Sugar-Sweetened Beverages in Infants' Diets: A Randomized Controlled Trial. 2023. 62(4):276–87. | Intervention/exposure
146 | Gomez-Martin M, Herrero-Morin D, Solis G, Longitudinal Study Depicting Differences in Complementary Feeding and Anthropometric Parameters in Late Preterm Infants up to 2 Years of Age. Nutrients. 2021. 13(3):982.33803743 | Intervention/exposure, Health status
147 | Goncalves VSS, Silva SA, Andrade RCS, Spaniol AM, Nilson EAF, Moura IF. Food intake and underweight markers in children under 6 months old monitored via the Food and Nutrition Surveillance System, Brazil, 2015. Epidemiol Serv Saude. 2019. 28(2):e2018358. | Study design
148 | Goyena EA, Barba CVC, Talavera MTM, Paunlagui MM, Rola AC, Tandang NA. Effects of micronutrient powder and complementary food blend on growth and micronutrient status of Filipino rural children: a randomised controlled trial. Malays J Nutr. 2018. 24(4):475–492. | Country
149 | Graf MD, Karp SM, Lutenbacher M, Wasser H, Bushaw A, Dietrich MS. Clinical strategies for addressing obesity in infants and toddlers. Nurse Pract. 2021.46(2):28–33. | Study design
150 | Graham GG, MacLean WC, Jr, Lopez de Romana. Prolonged consumption by infants of wheatbased diets with and without casein or lysine supplementation. J Nutr. 1981. 111(11): 1917–27.6795322 | Intervention/exposure
151 | Granziera F, Guzzardi MA, lozzo P. Associations between the mediterranean diet pattern and weight status and cognitive development in preschool children. Nutrients. 2021. 13(11):3723. doi:10.3390/nu13113723.34835979 | Study design, Age at intervention/exposure
152 | Gregory JE, Paxton SJ, Brozovic AM. Maternal feeding practices predict fruit and vegetable consumption in young children. Results of a 12-month longitudinal study. Appetite. 2011. 57(1 ):167 172.21569809 | Intervention/exposure
153 | Gridneva Z, Rea A, Hepworth AR, Relationships between Breastfeeding Patterns and Maternal and Infant Body Composition over the First 12 Months of Lactation. Nutrients. 2018. 10(1 ):45.29303992 | Intervention/exposure
154 | Grieken A, Renders CM, Gaar VM, Hirasing RA, Raat H. Associations between the home environment and children's sweet beverage consumption at 2-year follow-up: the ' Be active, eat right' study. Pediatr Obes. 2015. 10(2): 126–133.24903408 | Age at intervention/exposure
155 | Gross RS, Mendelsohn AL, Gross MB, Scheinmann R, Messito MJ. Randomized Controlled Trial of a Primary Care-Based Child Obesity Prevention Intervention on Infant Feeding Practices. J Pediatr. 2016. 174:171–177.e2.27113376 | Intervention/exposure
156 | Guedes JRD, H/1=o"/felmann DA, Madruga FP, Associated factors with dietary patterns among children under 2 years of age: A study in childcare centres and homes of South Brazil. J Nutr Sci. 2021. 10:e37.35401975 | Study design
157 | Guerrero AD, Mao C, Fuller B, Bridges M, Franke T, Kuo AA. Racial and Ethnic Disparities in Early Childhood Obesity: Growth Trajectories in Body Mass Index. Journal of racial and ethnic health disparities. 2016. 3(1):129–137.26896112 | Age at intervention/exposure
158 | Gunderson EP, Greenspan LC, Faith MS, Hurston, SR, Quesenberry CP, Jr, Swift Offspring Study Investigators. Breastfeeding and growth during infancy among offspring of mothers with gestational diabetes mellitus: a prospective cohort study. Pediatr Obes. 2018. 13(8):492–504.29691992 | Intervention/exposure, Outcome
159 | Gunnell L, Neher J, Safranek S, Guthmann R. Does breastfeeding affect the risk of childhood obesity?. J Fam Pract. 2016. 65(12):931–932.28149981 | Study design, Publication status
160 | G/1=u"/nther AL, Remer T, Kroke A, Buyken AE. Early protein intake and later obesity risk: which protein sources at which time points throughout infancy and childhood are important for body mass index and body fat percentage at 7 y of age?. Am J Clin Nutr. 2007. 86(6): 1765–72.18065597 | Intervention/exposure
161 | Haas JD, Rivera-Dommarco J. The Effects of Improved Nutrition in Early Childhood on Adolescent and Early Adulthood Body Size, Composition, Maturity, and Function: results From the First INCAP Follow-Up Study. Food Nutr Bull. 2020. 41(1_suppl):S23–S30.32522125 | Country
162 | Hakanen M, Lagstr/1=o"/m H, Kaitosaari T, Development of overweight in an atherosclerosis prevention trial starting in early childhood. The STRIP study. Int J Obes (Lond). 2006. 30(4):618–626.16446743 | Intervention/exposure
163 | Haro-Mora JJ, Garc/1=i'/a-Escobar E, Porras N, Children whose diet contained olive oil had a lower likelihood of increasing their body mass index Z-score over 1 year. Eur J Endocrinol. 2011. 165(3):435–439.21715417 | Age at intervention/exposure
164 | Harrison M, Brodribb W, Davies PSW, Hepworth J. Impact of Maternal Infant Weight Perception on Infant Feeding and Dietary Intake. Matern Child Health J. 2018. 22(8):1135–1145.29497984 | Study design
165 | Harrison M, Brodribb W, Davies PSW, Hepworth J. Relationships between parental feeding practices, infant weight concern, infant dietary behaviour and body weight: Findings from the Feeding A Baby (FAB) Study. Obes Res Clin Pract. 2019. 13(1):86–86. | Publication status
166 | Hasnain SR, Singer MR, Bradlee ML, Moore LL. Beverage intake in early childhood and change in body fat from preschool to adolescence. Childhood Obesity. 2014. 10(1):42–49.24450382 | Age at intervention/exposure
167 | Hastuti, Hadju V, Citrakesumasari, Maddeppungeng M. Stunting prevalence and its relationship to birth length of 18-23 months old infants in Indonesia. Enferm Clin. 2020. 30:205–209. | Country
168 | Haszard JJ, Diana A, Daniels L, Houghton LA, Gibson RS. Development of a nutrient quality score for the complementary diets of Indonesian infants and relationships with linear growth and stunting: a longitudinal analysis. Br J Nutr. 2019. 122(1):71–77.30975226 | Country
169 | Haszard JJ, Russell CG, Byrne RA, Taylor RW, Campbell KJ. Early maternal feeding practices: Associations with overweight later in childhood. Appetite. 2019. 132:91–96.30308224 | Intervention/exposure
170 | Hazrati S, Khan F, Huddleston K, Clinical and social factors associated with excess weight in Hispanic and non-Hispanic White children. Pediatr Res. 2019. 85(3):256–261.30643189 | Study design, Intervention/exposure
171 | Headey D, Hirvonen K, Hoddinott J. Animal Sourced Foods and Child Stunting. Am J Agric Econ. 2018. 100(5):1302–1319.33343003 | Study design
172 | Heerman WJ, Sneed NM, Sommer EC, Ultra-processed food consumption and BMI-Z among children at risk for obesity from low-income households. Pediatr Obes. 2023. 18(8):e13037.37070567 | Age at intervention/exposure
173 | Helle C, Hillesund ER, Wills AK, Overby NC. Evaluation of an eHealth intervention aiming to promote healthy food habits from infancy -the Norwegian randomized controlled trial Early Food for Future Health. Int J Behav Nutr Phys Act. 2019. 16(1):1.30606197 | Intervention/exposure
174 | Helle C, Hillesund ER, Wills AK, Overby NC. Examining the effects of an eHealth intervention from infant age 6 to 12 months on child eating behaviors and maternal feeding practices one year after cessation: The Norwegian randomized controlled trial Early Food for Future Health. PLoS One. 2019. 14(8):e0220437.31442241 | Intervention/exposure, Outcome
175 | Herath MP, Ahuja KDK, Beckett JM, Jayasinghe S, Byrne NM, Hills AP. Determinants of Infant Adiposity across the First 6 Months of Life: Evidence from the Baby-bod study. J Clin Med. 2021. 10(8):1770.33921680 | Intervention/exposure
176 | Herber C, Bogler L, Subramanian SV, Vollmer S. Association between milk consumption and child growth for children aged 6-59 months. Sci Rep. 2020. 10(1):6730.32317668 | Study design
177 | Herr RM, De Bock F, Diehl K, Associations of individual factors and early childhood education and care (ECEC) centres characteristics with preschoolers' BMI in Germany. BMC Public Health. 2022. 22(1):1415.35883054 | Age at intervention/exposure
178 | Hesketh KD, Salmon J, McNaughton SA, Long-term outcomes (2 and 3.5 years postintervention) of the INFANT early childhood intervention to improve health behaviors and reduce obesity: Cluster randomised controlled trial follow-up. Int J Behav Nutr Phys Act. 2020. 17(1):95.32711523 | Intervention/exposure
179 | Hoffman DJ. Nutrients in Complementary Feeding Protect Against Wasting, but Not Stunting: Results from a Multi-Country Longitudinal Cohort Study. J Nutr. 2021. 151(1):5–6.33245106 | Study design
180 | Hoffmann J, Gunther J, Stecher L, Infant growth during the first year of life following a pregnancy lifestyle intervention in routine care-Findings from the cluster-randomised GeliS trial. Pediatr Obes. 2021. 16(2):e12705.32725809 | Intervention/exposure
181 | Hohman EE, Paul IM, Birch LL, Savage JS. INSIGHT responsive parenting intervention is associated with healthier patterns of dietary exposures in infants. Obesity (Silver Spring). 2017. 25(1):185–191.28008749 | Intervention/exposure
182 | Hollen LI, Din Zu, Jones LR, Emond AM, Emmett P. Are diet and feeding behaviours associated with the onset of and recovery from slow weight gain in early infancy?. Br J Nutr. 2014. 111(9):1696–704.24502920 | Study design
183 | Hollis JL, Crozier SR, Inskip HM, Age at introduction of solid foods and feeding difficulties in childhood: findings from the Southampton Women's Survey. Br J Nutr. 2016. 116(4):743–50.27356464 | Outcome
184 | Horan MK, Donnelly JM, McGowan CA, Gibney ER, McAuliffe FM. The association between maternal nutrition and lifestyle during pregnancy and 2-year-old offspring adiposity: analysis from the ROLO study. Journal of Public Health (Germany). 2016. 24(5):427–436. | Intervention/exposure
185 | Horodynski MA, Pierce SJ, Reyes-Gastelum D, Olson B, Shattuck M. Feeding Practices and Infant Growth: Quantifying the Effects of Breastfeeding Termination and Complementary Food Introduction on BMI z-Score Growth Velocity through Growth Curve Models. Child Obes. 2017. 13(6):490–498.28767287 | Intervention/exposure
186 | Horst CH, Obermann-de Boer GL, Kromhout D. Type of milk feeding and nutrient intake during infancy. The Leiden Pre-School Children Study. Acta Paediatr Scand. 1987. 76(6):865–871.3501226 | Outcome
187 | Hose AJ, Pagani G, Karvonen AM, Excessive Unbalanced Meat Consumption in the First Year of Life Increases Asthma Risk in the PASTURE and LUKAS2 Birth Cohorts. Front Immunol. 2021. 12:651709.33986744 | Outcome
188 | Hu J, Aris IM, Lin PD, Longitudinal associations of modifiable risk factors in the first 1000 days with weight status and metabolic risk in early adolescence. Am J Clin Nutr. 2020. 113(1):113–22. | Intervention/exposure
189 | Huang H, Gao Y, Zhu N, The Effects of Breastfeeding for Four Months on Thinness, Overweight, and Obesity in Children Aged 3 to 6 Years: A Retrospective Cohort Study from National Physical Fitness Surveillance of Jiangsu Province, China. Nutrients. 2022. 14(19):4154. doi:10.3390/nu14194154.36235805 | Study design, Intervention/exposure
190 | Huang H, Wan Mohamed Radzi CW, Salarzadeh Jenatabadi H. Family Environment and Childhood Obesity: A New Framework with Structural Equation Modeling. Int J Environ Res Public Health. 2017. 14(2):181.28208833 | Study design
191 | Huang J, Zhang Z, Wu Y, Early feeding of larger volumes of formula milk is associated with greater body weight or overweight in later infancy. Nutr J. 2018. 17(1):12.29368651 | Intervention/exposure
192 | Huang SK, Chih MH. Increased Breastfeeding Frequency Enhances Milk Production and Infant Weight Gain: Correlation with the Basal Maternal Prolactin Level. Breastfeed Med. 2020. 15(10):639 645.32799538 | Intervention/exposure
193 | Hughes SO, Power TG, Beck AD, Twelve-Month Efficacy of an Obesity Prevention Program Targeting Hispanic Families With Preschoolers From Low-Income Backgrounds. J Nutr Educ Behav. 2021. 53(8):677–690.34148764 | Age at intervention/exposure
194 | Huh SY, Rifas-Shiman SL, Rich-Edwards JW, Taveras EM, Gillman MW. Prospective association between milk intake and adiposity in preschool-aged children. J Am Diet Assoc. 2010. 110(4):563 70.20338282 | Age at intervention/exposure
195 | Huvinen E, Tuomaala A- K, Bergman PH, Ascending Growth is Associated with Offspring Adiposity in Pregnancies Complicated with Obesity or Gestational Diabetes. J Clin Endocrinol Metab. 2021. 106(5):E1993. doi:10.1210/clinem/dgaa979.33524144 | Intervention/exposure
196 | Hyczko AV, Ruggiero CF, Hohman EE, Sex Differences in Maternal Restrictive Feeding Practices in the Intervention Nurses Start Infants Growing on Healthy Trajectories Study. Acad Pediatr. 2021. 21 (6):1070–1076.34020105 | Intervention/exposure
197 | lannotti LL, Chapnick M, Nicholas J, Egg intervention effect on linear growth no longer present after two years. Matern Child Nutr. 2020. 16(2):e12925.31849201 | Directness of experimental studies
198 | lannotti LL, Lutter CK, Stewart CP, Eggs in Early Complementary Feeding and Child Growth: A Randomized Controlled Trial. Pediatrics. 2017. 140(1):e20163459.28588101 | Directness of experimental studies
199 | Iguacel I, Chung A, Gearon E, Moreno LA, Peeters A, Backholer K. Influence of early-life risk factors on socioeconomic inequalities in weight gain. J Public Health (Oxf). 2018. 40(4):e447–e455.29608712 | Intervention/exposure
200 | Iguacel I, Monje L, Cabero MJ, Feeding patterns and growth trajectories in breast-fed and formula-fed infants during the introduction of complementary food. Nutr Hosp. 2019. 36(4):777–785.31271292 | Intervention/exposure
201 | Irct20190705044103N, . Smartphone-based maternal education directed at complementary feeding among malnourished children below 3 years of age in Urmia, Iran. http://www.who.int/trialsearch/Trial2.aspx?TriallD=IRCT20190705044103N1.2019. | Publication status
202 | Isong IA, Rao SR, Bind MA, Avenda/1=n~/o M, Kawachi I, Richmond TK. Racial and ethnic disparities in early childhood obesity. Pediatrics. 2018. 141 (1):e20170865.29269386 | Intervention/exposure
203 | Iszatt N, Stigum H, Govarts E, Perinatal exposure to dioxins and dioxin-like compounds and infant growth and body mass index at seven years: A pooled analysis of three European birth cohorts. Environ Int. 2016. 94:399–407.27311652 | Intervention/exposure
204 | Jansen EC, Kasper N, Lumeng JC, Changes in household food insecurity are related to changes in BMI and diet quality among Michigan Head Start preschoolers in a sex-specific manner. Soc Sci Med. 2017. 181:168–176.28407601 | Age at intervention/exposure
205 | Jansen PW, Derks IPM, Batenburg A, Using Food to Soothe in Infancy is Prospectively Associated with Childhood BMI in a Population-Based Cohort. J Nutr. 2019. 149(5):788–794.30989177 | Intervention/exposure
206 | Jard/1=i'/ C, Aranda N, Bedmar C, Consumption of free sugars and excess weight in infants. A longitudinal study. Anales de Pediatria. 2019. 90(3):165–172.29773523 | Intervention/exposure
207 | Jayanti R, Yanuaringsih GP, Olivia N, Jundapri K, Ariandini S, Munir R. Determinants of stunting in indonesian toddlers. Indian Journal of Forensic Medicine and Toxicology. 2021. 15(3):3954–3959. | Study design
208 | Jen V, Braun KVE, Karagounis LG, Longitudinal association of dietary protein intake in infancy and adiposity throughout childhood. Clinical Nutrition. 2019. 38(3):1296–1302.29914777 | Intervention/exposure
209 | Jia N, Gu G, Zhao L, Longitudinal study of breastfeeding and growth in 0-6 month infants. Asia Pac J Clin Nutr. 2018. 27(6):1294–1301.30485929 | Intervention/exposure
210 | Jiang H, Li M, Wen LM, A Community-Based Short Message Service Intervention to Improve Mothers' Feeding Practices for Obesity Prevention: Quasi-Experimental Study. JMIR Mhealth Uhealth. 2019. 7(6):e13828.31162133 | Intervention/exposure
211 | Jiang HJ, Li ML, Wen LMW, Effect of short message service intervention on children's BMI at 12 and 24 months and factors associated with BMI at 24 months: a community-based intervention in Shanghai, China. Obesity reviews. 2016. 17(Suppl 2):155. | Intervention/exposure, Outcome
212 | Joanna Briggs Institute. Effective dietary interventions for managing overweight and obesity in children. Nurs N Z. 2007. 13(5):30–31. | Study design
213 | Johansson U, Ohlund I, Hernell O, Lonnerdal B, Lindberg L, Lind T. Protein-Reduced Complementary Foods Based on Nordic Ingredients Combined with Systematic Introduction of Taste Portions Increase Intake of Fruits and Vegetables in 9 Month Old Infants: A Randomised Controlled Trial. Nutrients. 2019. 11 (6): 1255.31159495 | Intervention/exposure
214 | Johansson U, Ohlund I, Lindberg L, Hernell O, Lonnerdal B, Lind T. A randomised, controlled trial of a Nordic, protein-reduced complementary diet: effects on dietary intake, biomarkers and growth until 18 months of age. J Pediatr Gastroenterol Nutr. 2022. 74(2):914–915. | Publication status
215 | Jones LR, Emmett PM, Hays NP, Shahkhalili Y, Taylor CM. Association of Nutrition in Early Childhood with Body Composition and Leptin in Later Childhood and Early Adulthood. Nutrients. 2021. 13(9):3264.34579140 | Intervention/exposure
216 | Jones LJ, VanWassenhove-Paetzold J, Thomas K, Impact of a fruit and vegetable prescription program on health outcomes and behaviors in young navajo children. Curr Dev in Nutr. 2020. 4(8):nzaa109. | Age at intervention/exposure
217 | Jones SW, Lee M, Brown A. Spoonfeeding is associated with increased infant weight but only amongst formula-fed infants. Matern Child Nutr. 2020. 16(3):e12941.31943799 | Intervention/exposure
218 | Kaar JL, Sauder KA, Shapiro AL, Infant Feeding Practices In a Diverse Group of Women: The Healthy Start Study. Clin Med Insights Pediatr. 2019. 13:1179556518824362.30718970 | Intervention/exposure, Outcome
219 | Kaar JL, Schmiege SJ, Vadiveloo M, Simon SL, Tovar A. Sleep duration mediates the relationship between health behavior patterns and obesity. Sleep Health. 2018. 4(5):442–447.30241659 | Study design, Intervention/exposure, Age at intervention/exposure
220 | Kalhoff H, Mesch CM, Stimming M, Effects of LC-PUFA supply via complementary food on infant development—a food based intervention (RCT) embedded in a total diet concept. Eur J Clin Nutr. 2020. 74(5):682–690.31383978 | Outcome
221 | Kang S, Lee SW, Cha HR, Kim SH, Han MY, Park MJ. Growth in Exclusively Breastfed and Non-exclusively Breastfed Children: Comparisons with WHO Child Growth Standards and Korean National Growth Charts. J Korean Med Sci. 2021. 36(47):e315.34873884 | Study design, Intervention/exposure
222 | Kartasurya MI, Pangestuti DR, Kusumawati A, Cadres outreach program to mothers improve nutritional status of under Two Year Old Children. Indian Journal of Public Health Research and Development. 2019. 10(3):917–922. | Intervention/exposure, Country
223 | Kasman M, Heuberger B, Mack-Crane W, Using a Microsimulation of Energy Balance to Explore the Influence of Prenatal Sugar-Sweetened Beverage Intake on Child BMI. Obesity. 2021. 29(4):731–739.33619862 | Age at intervention/exposure
224 | Katan MB, e Ruyter JC, Kuijper LD, Chow CC, Hall KD, Olthof MR. Impact of Masked Replacement of Sugar-Sweetened with Sugar-Free Beverages on Body Weight Increases with Initial BMI: secondary Analysis of Data from an 18 Month Double-Blind Trial in Children. PLoS One. 2016. 11(7):e0159771.27447721 | Age at intervention/exposure
225 | Kattelmann KK, Ho M, Specker BL. Effect of timing of introduction of complementary foods on iron and zinc status of formula fed infants at 12, 24, and 36 months of age. J Am Diet Assoc. 2001. 101(4):443–447.11320951 | Outcome
226 | Kaul P, Bowker SL, Savu A, Yeung RO, Donovan LE, Ryan EA. Association between maternal diabetes, being large for gestational age and breast-feeding on being overweight or obese in childhood. Diabetologia. 2019. 62(2):249–258.30421138 | Intervention/exposure
227 | Kavey RE. How sweet it is: sugar-sweetened beverage consumption, obesity, and cardiovascular risk in childhood. J Am Diet Assoc. 2010. 110(10):1456–60.20869483 | Study design
228 | Kavle JA, Flax VL, Abdelmegeid A, Factors associated with early growth in Egyptian infants: Implications for addressing the dual burden of malnutrition. Matern Child Nutr. 2016. 12(1):139–151.26373408 | Country
229 | Kay MC, Wasser H, Adair LS, Consumption of obesogenic foods in non-Hispanic black mother-infant dyads. Matern Child Nutr. 2018. 14(1):e12482.28627126 | Outcome
230 | Kelleher CC, Viljoen K, Khalil H, Longitudinal follow-up of the relationship between dietary intake and growth and development in the lifeways cross-generation cohort study 2001-2013. Proc Nutr Soc. 2014. 73(1):118–131.24300176 | Study design
231 | Kerr JA, Long C, Clifford SA, Early-life exposures predicting onset and resol of childhood overweight or obesity. Arch Dis Child. 2017. 102(10):922–929. | Intervention/exposure
232 | Kheir F, Feeley N, Maximova K, Drapeau V, Henderson M, Van Hulst A. Breastfeeding duration in infancy and dietary intake in childhood and adolescence. Appetite. 2021. 158:104999.33058954 | Intervention/exposure, Outcome
233 | Khor GL, Lee SS. Complementary Foods and Milk-Based Formulas Provide Excess Protein but Suboptimal Key Micronutrients and Essential Fatty Acids in the Intakes of Infants and Toddlers from Urban Settings in Malaysia. Nutrients. 2021. 13(7):2354.34371864 | Study design
234 | Kim JH, Lee SW, Lee JE, Ha EK, Han MY, Lee E. Breastmilk Feeding during the First 4 to 6 Months of Age and Childhood Disease Burden until 10 Years of Age. Nutrients. 2021. 13(8):2825.34444985 | Intervention/exposure
235 | Kim-Herrera EY, Ramírez-Silva I, Rodríguez-Oliveros G, Parental Feeding Styles and Their Association With Complementary Feeding Practices and Growth in Mexican Children. Front Pediatr. 2021. 9:786397.34993164 | Intervention/exposure, Outcome
236 | Kiraly CM, Turk MT, Kalarchian MA, Shaffer C. Exploring Factors Linked to Weight Status in Salvadoran Infants. Hisp Health Care Int. 2021. 19(2):95–104.32975445 | Study design, Country
237 | Kittisakmontri K, Lanigan J, Wells JCK, Manowong S, Kaewarree S, Fewtrell M. Quantity and Source of Protein during Complementary Feeding and Infant Growth: Evidence from a Population Facing Double Burden of Malnutrition. Nutrients. 2022. 14(19):3948.36235599 | Intervention/exposure
238 | Kittisakmontri K, Lanigan J, Fewtrell M. Potential mediators of associations between protein intake from different food sources and infant growth during the complementary feeding period; evidence from a middle-income country. J Pediatr Gastroenterol Nutr. 2022. 74:991–992. | Publication status
239 | Kjaer TW, Faurholt-Jepsen D, Medrano R, Higher Birthweight and Maternal Pre-pregnancy BMI Persist with Obesity Association at Age 9 in High Risk Latino Children. J Immigr Minor Health. 2019. 21(1):89–97.29397484 | Intervention/exposure
240 | Kloeblen-Tarver AS. Fruit juice consumption not related to growth among preschool-aged children enrolled in the WIC program...including commentary by Skinner JD and Carruth BR. J Am Diet Assoc. 2001. 101(9):996–996.11573767 | Study design
241 | Kong KL, Fazzino TL, Rohde KM, Morris KS. The Prevalence of Hyperpalatable Baby Foods and Exposure During Infancy: A Preliminary Investigation. Front Psychol. 2021. 12:614607.33927666 | Study design, Outcome
242 | Kostecka M, Jackowska I, Kostecka J. Factors Affecting Complementary Feeding of Infants. A Pilot Study Conducted after the Introduction of New Infant Feeding Guidelines in Poland. Nutrients. 2020. 13(1):61.33379149 | Outcome
243 | Kramer MS, Davies N, Oken E, Infant feeding and growth: putting the horse before the cart. Am J Clin Nutr. 2018. 107(4):635–639.29635502 | Intervention/exposure
244 | Krasevec J, An X, Kumapley R, Begin F, Frongillo EA. Diet quality and risk of stunting among infants and young children in low- and middle-income countries. Matern Child Nutr. 2017. 13 Suppl 2:e12430.29032628 | Study design
245 | Kuniyoshi Y, Kikuya M, Matsubara H, Association of Feeding Practice with Childhood Overweight and/or Obesity in Affected Areas Before and After the Great East Japan Earthquake. Breastfeed Med. 2019. 14(6):382–389.30985196 | Study design, Intervention/exposure
246 | Kusumawardani DA, Luthfiyana NU. Child feeding practices and stunting: A case-control study in jember regency of Indonesia. Indian Journal of Public Health Research and Development. 2020. 11(6):226–231. | Study design, Country
247 | Laadjel R, Taleb S. Factors associated with the age of initiation of food diversification in children aged 6 to 60 months in eastern Algeria: Correlation to nutritional status. Nutrition Clinique et Metabolisme. 2020. 34(3):238–247. | Study design, Language
248 | Lagström H, Seppänen R, Jokinen E, Influence of dietary fat on the nutrient intake and growth of children from 1 to 5 y of age: the Special Turku Coronary Risk Factor Intervention Project. Am J Clin Nutr. 1999. 69(3):516–23.10075339 | Intervention/exposure
249 | Lahiri A, Chakraborty A. Predictors of Weight Velocity in the First 6 Months of Life in a Rural Block of West Bengal: A Longitudinal Study. Indian J Community Med. 2019. 44(2):92–96.31333283 | Country
250 | Laitinen J, Pietiläinen K, Wadsworth M, Sovio U, Järvelin MR. Predictors of abdominal obesity among 31-y-old men and women born in Northern Finland in 1966. Eur J Clin Nutr. 2004. 58(1):180–90.14679384 | Age at intervention/exposure
251 | Lakshman R, Sharp SJ, Whittle F, Randomised controlled trial of a theory-based behavioural intervention to reduce formula milk intake. Arch Dis Child. 2018. 103(11):1054–1060.29760009 | Intervention/exposure
252 | Lapinleimu H, Jokinen E, Myyrinmaa A, Individualized dietary counselling of families: serum cholesterol concentration and growth of children aged 7-13 months. Acta Paediatr. 1994. 83(4):383–8.8025393 | Intervention/exposure
253 | Lapinleimu H, Viikari J, Jokinen E, Prospective randomised trial in 1062 infants of diet low in saturated fat and cholesterol. Lancet. 1995. 345(8948):471–6.7861873 | Intervention/exposure
254 | Larsson MW, Lind MV, Larnkjaer A, Excessive Weight Gain Followed by Catch-Down in Exclusively Breastfed Infants: An Exploratory Study. Nutrients. 2018. 10(9):1290.30213080 | Intervention/exposure
255 | Laws RA, Denney-Wilson EA, Taki S, Key Lessons and Impact of the Growing Healthy mHealth Program on Milk Feeding, Timing of Introduction of Solids, and Infant Growth: Quasi-Experimental Study. JMIR Mhealth Uhealth. 2018. 6(4):e78.29674313 | Intervention/exposure, Outcome
256 | Lee H, Zavaleta N, Chen SY, Lonnerdal B, Slupsky C. Effect of bovine milk fat globule membranes as a complementary food on the serum metabolome and immune markers of 6-11-month-old Peruvian infants. NPJ Sci Food. 2018. 2:6.31304256 | Intervention/exposure, Outcome
257 | Lee I, Bang K- S, Moon H, Kim J. Risk Factors for Obesity Among Children Aged 24 to 80 months in Korea: A Decision Tree Analysis. J Pediatr Nurs. 2019. 46:e15–e23.30773305 | Study design, Age at intervention/exposure
258 | Lee WT, Leung SS, Lui SS, Lau J. Relationship between long-term calcium intake and bone mineral content of children aged from birth to 5 years. Br J Nutr. 1993. 70(1):235–48.8399105 | Intervention/exposure
259 | Leermakers ETM, van den Hooven EH, Franco OH, A priori and a posteriori derived dietary patterns in infancy and cardiometabolic health in childhood: The role of body composition. Clin Nutr. 2018. 37(5):1589–1595.28830701 | Outcome
260 | Leung SS, Chan SM, Lui S, Lee WT, Davies DP. Growth and nutrition of Hong Kong children aged 0-7 years. J Paediatr Child Health. 2000. 36(1):56–65.10723693 | Intervention/exposure
261 | Leung TF, Ulfman LH, Chong MKC, A randomized controlled trial of different young child formulas on upper respiratory and gastrointestinal tract infections in Chinese toddlers. Pediatr Allergy Immunol. 2020. 31(7):745–754.32426882 | Outcome, Comparator
262 | Lev-Ari L, Bachner-Melman R, Zohar AH, Ebstein R, Mankuta D. Weight gain, feeding and eating in the first year of life of babies of smoking and non-smoking mothers. Early Hum Dev. 2019. 140:104889.31670174 | Intervention/exposure
263 | Levine AA. Excessive fruit juice consumption: how can something that causes failure to thrive be associated with obesity?. J Pediatr Gastroenterol Nutr. 1997. 25(5):554–5.9360213 | Study design
264 | Li Ming W. A bottle-weaning counselling intervention for parents of 12-month-old infants reduces bottle use at age 24 months but has no effect on child weight. Evidence based nursing. 2015. 18(1):14–14.24858441 | Study design, Intervention/exposure
265 | Lim SX, Toh JY, van Lee L, Food Sources of Energy and Macronutrient Intakes among Infants from 6 to 12 Months of Age: The Growing Up in Singapore Towards Healthy Outcomes (GUSTO) Study. Int J Environ Res Public Health. 2018. 15(3):488.29534442 | Outcome
266 | Linares AM, Rayens MK, Moylan JS, Miller CS. Degree of Agreement Between Infant Serum and Salivary Concentration of Leptin and Adiponectin and Its Association With Infants' Feeding. Biol Res Nurs. 2021. 23(3):541. doi:10.1177/1099800420973366.33251850 | Intervention/exposure, Outcome
267 | Lind MV, Larnkjær A, Mølgaard C, Michaelsen KF. Early Nutrition and Its Effect on Growth, Body Composition, and Later Obesity. World Rev Nutr Diet. 2017. 116:118–133.28171860 | Study design, Publication status
268 | Liu J, Liu J, Frongillo EA, Jr, Body mass index trajectories during the first year of life and their determining factors. Am J Hum Biol. 2019. 31(1):e23188.30499610 | Intervention/exposure
269 | Lopes AF, Rocha EMB, da Silva JPC, Nascimento VG, Bertoli C, Leone C. Breastfeeding, complementary food introduction and overweight in preschool children. Arch Latinoam Nutr. 2016. 66(3):195–200.29870606 | Study design, Language
270 | Lopez de Romaña G, Graham GC, Madrid S, MacLean WC. Prolonged consumption of potato-based diets by infants and small children. J Nutr. 1981. 111(8):1430–6.7264773 | Country
271 | Lovell AL, Milne T, Matsuyama M, Protein Intake, IGF-1 Concentrations, and Growth in the Second Year of Life in Children Receiving Growing Up Milk - Lite (GUMLi) or Cow's Milk (CM) Intervention. Front Nutr. 2021. 8:666228.34179057 | Duplicate data
272 | Luque V, Escribano J, Closa-Monasterolo R, Unhealthy dietary patterns established in infancy track to mid-childhood: The EU childhood obesity project. J Nutr. 2018. 148(5):752–759.29982656 | Outcome
273 | Ma JQ, Zhou LL, Hu YQ, Liu SS, Sheng XY. Association between feeding practices and weight status in young children. BMC Pediatr. 2015. 15:97.26306490 | Intervention/exposure
274 | Machuca H, Arevalo S, Hackley B, Well Baby Group Care: Evaluation of a Promising Intervention for Primary Obesity Prevention in Toddlers. Child Obes. 2016. 12(3):171–178.27035857 | Intervention/exposure
275 | Maciel BLL, Costa PN, Filho JQ, Higher Energy and Zinc Intakes from Complementary Feeding Are Associated with Decreased Risk of Undernutrition in Children from South America, Africa, and Asia. J Nutr. 2021. 151(1):170–178.32939530 | Country
276 | Madsen MTB, Biltoft-Jensen AP, Trolle E, Lauritzen L, Michaelsen KF, Damsgaard CT. Wholegrain intake, growth and metabolic markers in Danish infants and toddlers: a longitudinal study. Eur J Nutr. 2022. 61(7):3545. doi:10.1007/s00394-022-02902-2.35622136 | Study design, Intervention/exposure
277 | Magarey A, Kavian F, Scott JA, Markow K, Daniels L. Feeding Mode of Australian Infants in the First 12 Months of Life. J Hum Lact. 2016. 32(4):NP95–NP104.26416440 | Outcome
278 | Maier IB, Özel Y, Wagnerberger S, Bischoff SC, Bergheim I. Dietary pattern and leisure time activity of overweight and normal weight children in Germany: Sex-specific differences. Nutr J. 2013. 12(1):14.23320866 | Age at intervention/exposure
279 | MAL-ED Network Investigators. Childhood stunting in relation to the pre- and postnatal environment during the first 2 years of life: The MAL-ED longitudinal birth cohort study. PLoS Med. 2017. 14(10):e1002408. doi:10.1371/journal.pmed.1002408 29069076 | Country
280 | Malihi Z, Portch R, Hashemi L, Modifiable Early Childhood Risk Factors for Obesity at Age Four Years. Child Obes. 2021. 17(3):196–208.33595354 | Age at intervention/exposure
281 | Mallan KM, Fildes A, Magarey AM, Daniels LA. The Relationship between Number of Fruits, Vegetables, and Noncore Foods Tried at Age 14 Months and Food Preferences, Dietary Intake Patterns, Fussy Eating Behavior, and Weight Status at Age 3.7 Years. J Acad Nutr Diet. 2016. 116(4):630–637.26198582 | Duplicate data
282 | Mandal B, Powell LM. Child care choices, food intake, and children's obesity status in the United States. Econ Hum Biol. 2014. 14(1):50–61.24958453 | Age at intervention/exposure
283 | Mannan H, Sacre Y, Attieh R, Farah D. Infant-Feeding Patterns and the Effects of Early Introduction to Formula and Solid Foods on Childhood Overweight or Obesity among 10-Years-Olds in a Low Socioeconomic Area of Lebanon: An Exploratory Analysis. Children. 2022. 9(7):1030.35884013 | Study design
284 | Mannan H. Early Infant Feeding of Formula or Solid Foods and Risk of Childhood Overweight or Obesity in a Socioeconomically Disadvantaged Region of Australia: A Longitudinal Cohort Analysis. Int J Environ Res Public Health. 2018. 15(8):1685.30087304 | Intervention/exposure
285 | Mardali F, Hosseini-Baharanchi FS, Dehnad A, Shidfar F, Mohammadi S, Găman M- A. Comparison of the key modifiable factors in the first 1000 days predicting subsequent overweight and obesity in pre-school children in Tehran: A case control study. Br J Nutr. 2022. 128(5):955–63. doi:10.1017/S0007114521003937.34588008 | Study design
286 | Marshall TA, Eichenberger-Gilmore JM, Broffitt BA, Warren JJ, Levy SM. Dental caries and childhood obesity: roles of diet and socioeconomic status. Community Dent Oral Epidemiol. 2007. 35(6):449–58.18039286 | Study design
287 | Martin RM, Kramer MS, Patel R, Effects of Promoting Long-term, Exclusive Breastfeeding on Adolescent Adiposity, Blood Pressure, and Growth Trajectories: A Secondary Analysis of a Randomized Clinical Trial. JAMA Pediatr. 2017. 171(7):e170698.28459932 | Intervention/exposure
288 | Martinez S, Johannsen J, Gertner G, Effects of a home-based participatory play intervention on infant and young child nutrition: a randomised evaluation among low-income households in El Alto, Bolivia. BMJ Glob Health. 2018. 3(3):e000687. | Country
289 | Martorell R. History and Design of the INCAP Longitudinal Study (1969-1977) and Its Impact in Early Childhood. Food Nutr Bull. 2020. 41(1_suppl):S8–S22.32522124 | Study design
290 | Maskarinec JM, Li R, Kravets ME, Boone KM, Keim SA. Association of Infant Feeding Methods and Excess Weight from Birth to Age 6. Breastfeed Med. 2021. 16(9):750–8.33913744 | Intervention/exposure
291 | Mastroeni MF, Mastroeni SSBS, Czarnobay SA, Ekwaru JP, Loehr SA, Veugelers PJ. Breast-feeding duration for the prevention of excess body weight of mother-child pairs concurrently: a 2-year cohort study. Public Health Nutr. 2017. 20(14):2537–2548.28625232 | Intervention/exposure
292 | Maupomé G, Karanja N, Ritenbaugh C, Lutz T, Aickin M, Becker T. Dental caries in American Indian toddlers after a community-based beverage intervention. Ethn Dis. 2010. 20(4):444–50.21305835 | Intervention/exposure
293 | McCormick DP, Reyna L, Reifsnider E. Calories, Caffeine and the Onset of Obesity in Young Children. Acad Pediatr. 2020. 20(6):801–808.32081767 | Intervention/exposure, Outcome
294 | Meng Y, Zhou Y, Li H, Effectiveness of Growing-Up Milk Containing Only A2 β-Casein on Digestive Comfort in Toddlers: A Randomized Controlled Trial in China. Nutrients. 2023. 15(6):1313.36986042 | Directness of experimental studies
295 | Mennella JA, Reiter A, Brewer B, Pohlig RT, Stallings VA, Trabulsi JC. Early Weight Gain Forecasts Accelerated Eruption of Deciduous Teeth and Later Overweight Status during the First Year. J Pediatr. 2020. 225:174–181 e2.32553836 | Intervention/exposure, Outcome
296 | Mennella JA, Smethers AD, Decker JE, Delahanty MT, Stallings VA, Trabulsi JC. Effects of early weight gain velocity, diet quality, and snack food access on toddler weight status at 1.5 years: Follow-up of a randomized controlled infant formula trial. Nutrients. 2021. 13(11):3946. doi:10.3390/nu13113946.34836199 | Intervention/exposure, Outcome
297 | Messito MJ, Katzow MW, Mendelsohn AL, Gross RS. Starting Early Program Impacts on Feeding at Infant 10 Months Age: A Randomized Controlled Trial. Child Obes. 2020. 16(S1):S4. doi:10.1089/chi.2019.0236.31934788 | Outcome
298 | Misra S, Khor GL, Mitchell P, Haque S, Benton D. A pilot study to determine the short-term effects of milk with differing glycaemic properties on sleep among toddlers: A randomised controlled trial. BMC Pediatr. 2015. 15(1)79.26174581 | Outcome, Comparator
299 | Mohd Shukri NH, Wells J, Eaton S, Randomized controlled trial investigating the effects of a breastfeeding relaxation intervention on maternal psychological state, breast milk outcomes, and infant behavior and growth. Am J Clin Nutr. 2019. 110(1):121–130.31161202 | Intervention/exposure
300 | Mok E, Vanstone CA, Gallo S, Li P, Constantin E, Weiler HA. Diet diversity, growth and adiposity in healthy breastfed infants fed homemade complementary foods. Int J Obes (Lond). 2017. 41(5):776–782.28163319 | Intervention/exposure
301 | Montgomery M, Johnson P, Ewell P. A Comparative Analysis of Rural versus Urban Preschool Children's Sugar-Sweetened Beverage Consumption, Body Mass Index and Parent’s Weight Status. SAGE Open Nursing. 2022. 8:1–6. | Age at intervention/exposure
302 | Moore LL, Bradlee ML, Gao D, Singer MR. Effects of average childhood dairy intake on adolescent bone health. J Pediatr. 2008. 153(5):667–73.18701115 | Age at intervention/exposure
303 | Morandi A, Tommasi M, Soffiati F, Prevention of obesity in toddlers (PROBIT): a randomised clinical trial of responsive feeding promotion from birth to 24 months. Int J Obes (Lond). 2019. 43(10):1961–1966.31270429 | Intervention/exposure
304 | Mora-Urda AI, Acevedo P, Montero Lopez MP. Relationship between prenatal and postnatal conditions and accelerated postnatal growth. Impact on the rigidity of the arterial wall and obesity in childhood. J Dev Orig Health Dis. 2019. 10(4):436–446.31347487 | Study design, Intervention/exposure
305 | Morgan EJ, Heath ALM, Szymlek-Gay EA, Red meat and a fortified manufactured toddler milk drink increase dietary zinc intakes without affecting zinc status of New Zealand toddlers. J Nutr. 2010. 140(12):2221–2226.20980643 | Outcome
306 | Morgan K, Zhou SM, Hill R, Lyons RA, Paranjothy S, Brophy ST. Identifying prenatal and postnatal determinants of infant growth: A structural equation modelling based cohort analysis. Int J Environ Res Public Health. 2021. 18(19):10265.34639581 | Study design
307 | Morgan RE. Does consumption of high-fructose corn syrup beverages cause obesity in children?. Pediatr Obes. 2013. 8(4):249–254.23630060 | Study design
308 | Morgen CS, Angquist L, Baker JL, Andersen AN, Sorensen TIA, Michaelsen KF. Breastfeeding and complementary feeding in relation to body mass index and overweight at ages 7 and 11 y: a path analysis within the Danish National Birth Cohort. Am J Clin Nutr. 2018. 107(3):313–322.29566190 | Intervention/exposure
309 | Moschonis G, de Lauzon-Guillain B, Jones L, The effect of early feeding practices on growth indices and obesity at preschool children from four European countries and UK schoolchildren and adolescents. Eur J Pediatr. 2017. 176(9):1181–1192.28711955 | Intervention/exposure
310 | Moumin NA, Netting MJ, Golley RK, Mauch CE, Makrides M, Green TJ. Usual Nutrient Intake Distribution and Prevalence of Inadequacy among Australian Children 0-24 Months: Findings from the Australian Feeding Infants and Toddlers Study (OzFITS) 2021. Nutrients. 2022. 14(7):1381. doi:10.3390/nu14071381.35405994 | Study design, Outcome
311 | Muhsen K, Na'amnih W, Goldsmith R, Associations of Feeding Practices in Early Life and Dietary Intake at School Age with Obesity in 10- to 12-Year-Old Arab Children. Nutrients. 2021. 13(6):2106.34205416 | Intervention/exposure
312 | Murakami K, Miyake Y, Sasaki S, Tanaka K, Arakawa M. Dietary glycemic index and glycemic load in relation to risk of overweight in Japanese children and adolescents: The Ryukyus Child Health Study. Int J Obes. 2011. 35(7):925–936. | Study design
313 | Muslihah N, Khomsan A, Briawan D, Riyadi H. Complementary food supplementation with a small-quantity of lipid-based nutrient supplements prevents stunting in 6-12-month-old infants in rural West Madura Island, Indonesia. Asia Pac J Clin Nutr. 2016. 25(Suppl 1):S36–S42.28027630 | Country
314 | Muslimatun S, Ari Wiradnyani LA. Dietary diversity, animal source food consumption and linear growth among children aged 1-5 years in Bandung, Indonesia: A longitudinal observational study. Br J Nutr. 2016. 116:S27–S35.26817493 | Country
315 | Nasution Z, Nurhayati I, Mahdiyah. The Effectiveness of Counseling and Mung Bean (Vigna radiata L) Premix Cookies as Complementary Food to Prevent Stunting. Curr Nutr Food Sci. 2023. 19(3):317. doi:10.2174/1573401318666220628102359. | Intervention/exposure
316 | Natale RA, Messiah SE, Asfour LS, Uhlhorn SB, Englebert NE, Arheart KL. Obesity Prevention Program in Childcare Centers: Two-Year Follow-Up. Am J Health Promot. 2017. 31(6):502–510.27630110 | Age at intervention/exposure
317 | Navarro P, Shivappa N, Hébert JR, Predictors of the dietary inflammatory index in children and associations with childhood weight status: A longitudinal analysis in the Lifeways Cross-Generation Cohort Study. Clinical Nutrition. 2020. 39(7):2169–2179.31606243 | Intervention/exposure, Age at intervention/exposure
318 | Nct. Complementary Weaning With Adult Food Typical of the Mediterranean Diet. https://clinicaltrials.gov/show/NCT05297357. 2022. | Publication status
319 | Nct. INFANT HEALTH- Promoting Mental Health and Healthy Weight in Infancy Through Sensitive Parenting. https://clinicaltrials.gov/show/NCT04601779. 2020. | Study design
320 | Neri D, Oliveira FLC, Carvalho AM, Somarriba GA, Scott GB, Miller TL. Associations Between Dietary Intake Before 6 Months of Age and Rapid Weight Gain Among HIV-exposed Uninfected Infants. J Pediatr Gastroenterol Nutr. 2017. 65(5):e104–e109.28422809 | Study design
321 | Neves AM, Madruga SW. Complementary feeding, consumption of industrialized foods and nutritional status of children under 3 years old in Pelotas, Rio Grande do Sul, Brazil, 2016: a descriptive study. Epidemiol Serv Saude. 2019. 28(1):e2017507.30970067 | Study design, Outcome
322 | Neves RO, Guimaraes LSP, Bosa VL, Infant processed food consumption and their interaction to breastfeeding and growth in children up to six months old. BMC Public Health. 2021. 21(1):1512.34353303 | Intervention/exposure
323 | Ngaisyah RD, Rohman A. Effect of fish consumption as a local food alternative for the reduction of stunting in toddlers. Pakistan Journal of Nutrition. 2019. 18(5):496–500. | Country
324 | Nguyen AN, Jen V, Jaddoe VWV, Diet quality in early and mid-childhood in relation to trajectories of growth and body composition. Clinical Nutrition. 2020. 39(3):845–852.30967308 | Intervention/exposure
325 | Nguyen AN, Santos S, Braun KVE, Voortman T. Carbohydrate intake in early childhood and body composition and metabolic health: Results from the generation R study. Nutrients. 2020. 12(7):1–11. | Intervention/exposure
326 | Nguyen AN, van Langeveld AWB, de Vries JHM, Dietary taste patterns in early childhood: the Generation R Study. Am J Clin Nutr. 2020. 113(1):63–9. | Study design, Intervention/exposure
327 | Nguyen T, Sokal-Gutierrez K, Lahiff M, Fernald L, Ivey SL. Early childhood factors associated with obesity at age 8 in Vietnamese children: The Young Lives Cohort Study. BMC Public Health. 2021. 21(1):301.33546643 | Country
328 | Nianogo RA, Wang MC, Wang A, Projecting the impact of hypothetical early life interventions on adiposity in children living in low-income households. Pediatr Obes. 2017. 12(5):398–405.27283011 | Age at intervention/exposure
329 | Nicklas TA, Farris RP, Smoak CG, Dietary factors relate to cardiovascular risk factors in early life. Bogalusa Heart Study. Arteriosclerosis. 1988. 8(2):193–9.3348759 | Intervention/exposure
330 | Nnanyelugo DO. Nutritional practices and food intake measurements and their relationship to socioeconomic grouping, location and their apparent nutritional adequacy in children. Appetite. 1982. 3(3):229–241.7159074 | Country
331 | Nobre IG, Jurema Santos GC, Santos de Almeida Oliveira TLP, Food consumption habits, gestational age and birth weight are predictive for children with excess weight: An analysis based on artificial neural network. Nutr Health. 2022. 2601060221124040. | Study design
332 | Noppornlertwong C, Tantibhaedhyangkul R. Comparison of growth, infections and feeding habits among formula-fed infants starting complementary feeding at 4 to 6 months old with those starting at 6 months old. Southeast Asian J Trop Med Public Health. 2016. 47(3):506–513.27405135 | Intervention/exposure
333 | Nur R, Rusydi M, Fajriah RN, Effects of family planning and baby care behavior on stunting in early married couples. Open Access Macedonian Journal of Medical Sciences. 2021. 9:467–473. | Study design, Country
334 | Obeidat B, Shriver B, Roman-Shriver C. Factors involved in the persistence of overweight among children enrolled in the Supplemental Food Program for Women, Infants, and Children. Matern Child Health J. 2010. 14(2):164–173.19229601 | Age at intervention/exposure
335 | Ochoa TJ, Baiocchi N, Valdiviezo G, Bullon V, Campos M, Llanos-Cuentas A. Evaluation of the efficacy, safety and acceptability of a fish protein isolate in the nutrition of children under 36 months of age. Public Health Nutr. 2017. 20(15):2819–2826.28805177 | Intervention/exposure
336 | Odar Stough C, Bolling C, Zion C, Stark LJ. Comparison of High and Normal Birth Weight Infants on Eating, Feeding Practices, and Subsequent Weight. Matern Child Health J. 2018. 22(12):1805–1814.30008043 | Study design
337 | Ohlund I, Hernell O, Hörnell A, Stenlund H, Lind T. BMI at 4 years of age is associated with previous and current protein intake and with paternal BMI. Eur J Clin Nutr. 2010. 64(2):138–45.19904295 | Intervention/exposure
338 | Okronipa H, Quezada-Sanchez AD, Johnson SL, Effect of Added Sugar on the Consumption of A Lipid-Based Nutrient Supplement Among 7-24-Month-Old Children. Nutrients. 2020. 12(10):3069.33049973 | Intervention/exposure, Outcome
339 | Okubo H, Crozier SR, Harvey NC, Diet quality across early childhood and adiposity at 6 years: The Southampton Women's Survey. Int J Obes. 2015. 39(10):1456–1462. | Intervention/exposure
340 | Ong YY, Pang WW, Michael N, Timing of introduction of complementary foods, breastfeeding, and child cardiometabolic risk: a prospective multiethnic Asian cohort study. Am J Clin Nutr. 2023. 117(1):83–92.36789947 | Intervention/exposure
341 | Onifade OM, Pringle KG, Rollo ME, Collins CE, Schumacher T, Rae KM. Dietary intake of Indigenous Australian infants and young children in the Gomeroi gaaynggal cohort. Nutr Diet. 2021. 78(4):386. doi:10.1111/1747-0080.12673.33908693 | Outcome
342 | Orlandi SP, Gonzalez-Chica DA, Buffarini R, Breastfeeding and complementary feeding associated with body composition in 18-19 years old adolescents in the 1993 Pelotas Birth Cohort. BMC Nutr. 2017. 3:84.32153860 | Country
343 | Ortega-Garcia JA, Kloosterman N, Alvarez L, Full Breastfeeding and Obesity in Children: A Prospective Study from Birth to 6 Years. Child Obes. 2018. 14(5):327–337.29912590 | Intervention/exposure
344 | Ortelan N, Augusto RA, Souza JMP. Factors associated with the evolution of weight of children in a supplementary feeding program. Rev Bras Epidemiol. 2019. 22:e190002.30810606 | Country, Health status
345 | O'Sullivan A, Farver M, Smilowitz JT. Correction to "The Influence of Early Infant-Feeding Practices on the Intestinal Microbiome and Body Composition in Infants". Nutr Metab Insights. 2015. 8(Suppl 1):87.27812287 | Study design, Publication status
346 | Pabayo R, Spence JC, Casey L, Storey K. Food consumption patterns: In preschool children. Canadian Journal of Dietetic Practice and Research. 2012. 73(2):66–71.22668839 | Age at intervention/exposure
347 | Padilha LL, Vianna EO, Vale ATM, Nascimento JXPT, da Silva AAM, Ribeiro CCC. Pathways in the association between sugar sweetened beverages and child asthma traits in the 2nd year of life: Findings from the BRISA cohort. Pediatr Allergy Immunol. 2020. 31(5):480–488.32160342 | Outcome
348 | Pahkala K, Laitinen TT, Niinikoski H, Effects of 20-year infancy-onset dietary counselling on cardiometabolic risk factors in the Special Turku Coronary Risk Factor Intervention Project (STRIP): 6-year post-intervention follow-up. Lancet Child Adolesc Health. 2020. 4(5):359–369.32333883 | Intervention/exposure
349 | Palacios C, Campos M, Gibby C, Melendez M, Lee JE, Banna J. Effect of a Multi-Site Trial using Short Message Service (SMS) on Infant Feeding Practices and Weight Gain in Low-Income Minorities. J Am Coll Nutr. 2018. 37(7):605–613.29708471 | Intervention/exposure
350 | Pang WW, McCrickerd K, Quah PL, Is breastfeeding associated with later child eating behaviours?. Appetite. 2020. 150:104653.32151607 | Intervention/exposure, Outcome
351 | Papanikolaou Y, Fulgoni VL, 3rd. Egg Consumption in Infants is Associated with Longer Recumbent Length and Greater Intake of Several Nutrients Essential in Growth and Development. Nutrients. 2018. 10(6):719.29867006 | Study design
352 | Papoutsou S, Savva SC, Hunsberger M, Timing of solid food introduction and association with later childhood overweight and obesity: The IDEFICS study. Matern Child Nutr. 2018. 14(1):e12471.28597536 | Study design
353 | Park SJ, Lee HJ. Exclusive breastfeeding and partial breastfeeding reduce the risk of overweight in childhood: A nationwide longitudinal study in Korea. Obes Res Clin Pract. 2018. 12(2):222–228.29396229 | Intervention/exposure
354 | Parkes A, Sweeting H, Young R, Wight D. Does parenting help to explain socioeconomic inequalities in children's body mass index trajectories? Longitudinal analysis using the Growing Up in Scotland study. J Epidemiol Community Health. 2016. 70(9):868–873.27056682 | Age at intervention/exposure
355 | Patel N, Dalrymple KV, Briley AL, Mode of infant feeding, eating behaviour and anthropometry in infants at 6-months of age born to obese women - a secondary analysis of the UPBEAT trial. BMC Pregnancy Childbirth. 2018. 18(1):355.30176807 | Study design, Intervention/exposure
356 | Pedroso J, Gubert MB. Cross-cultural adaptation and validation of the Infant Feeding Style Questionnaire in Brazil. PLoS One. 2021. 16(9):e0257991.34591911 | Intervention/exposure, Outcome
357 | Penny ME, Jimenez MM, Marin RM. Early rapid weight gain and subsequent overweight and obesity in middle childhood in Peru. BMC Obes. 2016. 3:55.27999679 | Age at intervention/exposure, Country
358 | Pereyra González I, Farías-Antúnez S, Buffarini R, Ultra-processed food consumption and the incidence of obesity in two cohorts of Latin-American young children: A longitudinal study. J Pediatr Nurs. 2023. 69:e120–e126. doi:10.1016/j.pedn.2022.12.018.36604255 | Intervention/exposure, Age at intervention/exposure
359 | Pereyra-González I, Mattei J. Combined intake of sugar-sweetened beverages and sugar-containing ultra-processed foods is associated with an increase in body mass index during early childhood. Pediatr Obes. 2023. 18(6):e13025.36945180 | Age at intervention/exposure
360 | Phelan S, Hagobian TA, Ventura A, ‘Ripple’ effect on infant zBMI trajectory of an internet-based weight loss program for low-income postpartum women. Pediatr Obes. 2019. 14(1):10.1111/ijpo.12456. | Intervention/exposure, Outcome
361 | Phillips F. Giving sound food advice for infants and toddlers. Nursing in Practice: The Journal for Today's Primary Care Nurse. 2018. | Study design
362 | Pia Chaparro M, Crespi CM, Anderson CE, Wang MC, Whaley SE. The 2009 special supplemental nutrition program for women, infants, and children (WIC) food package change and children's growth trajectories and obesity in Los Angeles County. Am J Clin Nutr. 2019. 109(5):1414–1421.31011750 | Intervention/exposure
363 | Pietrobelli A, Agosti M, MeNu Group. Nutrition in the First 1000 Days: Ten Practices to Minimize Obesity Emerging from Published Science. Int J Environ Res Public Health. 2017. 14(12):1491.29194402 | Study design
364 | Pillay L, Moodley D, Emel LM, Nkwanyana NM, Naidoo K. Growth patterns and clinical outcomes in association with breastfeeding duration in HIV exposed and unexposed infants: a cohort study in KwaZulu Natal, South Africa. BMC Pediatr. 2021. 21(1):183. doi:10.1186/s12887-021-02662-8.33874900 | Country
365 | Pimpin L, Jebb S, Johnson L, Wardle J, Ambrosini GL. Dietary protein intake is associated with body mass index and weight up to 5 y of age in a prospective cohort of twins. Am J Clin Nutr. 2016. 103(2):389–397.26718416 | Intervention/exposure
366 | Pimpin L, Jebb SA, Johnson L, Llewellyn C, Ambrosini GL. Sources and pattern of protein intake and risk of overweight or obesity in young UK twins. Br J Nutr. 2018. 120(7):820–829.30132433 | Intervention/exposure
367 | Pineros-Leano M, Grafft N, Aguayo L. Childhood obesity risk factors by race and ethnicity. Obesity. 2022. 30(8):1670–1680.35894074 | Age at intervention/exposure
368 | Pirilä S, Taskinen M, Viljakainen H, Infant Milk feeding influences adult bone health: A prospective study from birth to 32 years. PLoS One. 2011. 6(4):e19068.21556368 | Outcome
369 | Pluymen LPM, Wijga AH, Gehring U, Koppelman GH, Smit HA, van Rossem L. Breastfeeding and cardiometabolic markers at age 12: a population-based birth cohort study. Int J Obes (Lond). 2019. 43(8):1568–1577.30886238 | Intervention/exposure
370 | Pluymen LPM, Wijga AH, Gehring U, Koppelman GH, Smit HA, van Rossem L. Early introduction of complementary foods and childhood overweight in breastfed and formula-fed infants in the Netherlands: the PIAMA birth cohort study. Eur J Nutr. 2018. 57(5):1985–1993.29470690 | Intervention/exposure
371 | Qasem W, Azad MB, Hossain Z, Assessment of complementary feeding of Canadian infants: effects on microbiome & oxidative stress, a randomized controlled trial. BMC Pediatr. 2017. 17(1):54.28196533 | Directness of experimental studies
372 | Qu P, Mi B, Wang D, Association between the Infant and Child Feeding Index (ICFI) and nutritional status of 6- to 35-month-old children in rural western China. PLoS One. 2017. 12(2):e0171984.28207774 | Study design, Country
373 | Quinn L, Brady B, Ball E, Keaver L. An exploration into the influence of birthweight and breastfeedin status on the weight status of 3-year-olds in an Irish cohort. Ir J Med Sci. 2023. 192(1):199–205. doi:10.1007/s11845-022-02932-z.35118560 | Intervention/exposure
374 | Quyen PN, Nga HT, Chaffee B, Ngu T, King JC. Effect of maternal prenatal food supplementation, gestational weight gain, and breast-feeding on infant growth during the first 24 months of life in rural Vietnam. PLoS One. 2020. 15(6):e0233671.32584881 | Country
375 | Ra JS. Evaluation of a Mobile-based Maternal Feeding Education Program for Overweight Prevention in Infants. Asian Nurs Res. 2021. 15(2):136–43. | Intervention/exposure
376 | Rachmawati R, Novita R, Erwandi E, Fitriyaningsih E, Idroes R, Sasmita NR. The effectiveness of counseling on complementary food for mothers and supplementary feeding for increasing weight of breastfed babies (12-24 months of age) in the Aceh Besar District of Indonesia. Pakistan Journal of Nutrition. 2020. 19(6):279–284. | Study design, Intervention/exposure
377 | Rahmani S, Medise BE, Sjarif DR. Association between growing-up milk consumption and overweight and obesity in children aged 2-3 years. J Pediatr Gastroenterol Nutr. 2022. 74:1128–1128. | Study design
378 | Reifsnider E, McCormick DP, Cullen KW, Randomized Controlled Trial to Prevent Infant Overweight in a High-Risk Population. Acad Pediatr. 2018. 18(3):324–333.29277462 | Intervention/exposure
379 | Requejo AM, Navia B, Ortega MR, López-Sobaler AM, Quintas E, Gaspar MJ, Osorio O. The age at which meat is first included in the diet affects the incidence of iron deficiency and ferropenic anaemi in a group of pre-school children from Madrid. Int J Vitam Nutr Res. 1999. 69(2):127–131.10218150 | Study design
380 | Riaño-Galán I, Fernández-Somoano A, Rodríguez-Dehli C, Valvi D, Vrijheid M, Tardón A. Proatherogenic Lipid Profile in Early Childhood: Association with Weight Status at 4 Years and Parental Obesity. J Pediatr. 2017. 187:153–157.e2.28529017 | Intervention/exposure
381 | Richard SA, McCormick BJJ, Murray-Kolb LE, Characteristics associated with the transition to partial breastfeeding prior to 6 months of age: Data from seven sites in a birth cohort study. Matern Child Nutr. 2021. 17(3):e13166.33660928 | Intervention/exposure, Country
382 | Riedlova J, Paulova M, Vignerova J, The Low Prevalence of Overweight and Obesity in Czech Breastfed Infants and Young Children: An Anthropological Survey. Int J Environ Res Public Health. 2019. 16(21):4198.31671517 | Study design, Intervention/exposure
383 | Rikhotso IP, Faber M, Rothman M, Matsungo TM, Lombard C, Smuts CM. Nutritional status and psychomotor development in 12-18-month-old children in a post-intervention study. South African journal of clinical nutrition. 2022. 35(2):69–77. | Intervention/exposure
384 | Rivera JA, Shamah T, Villalpando S, Monterrubio E. Effectiveness of a large-scale iron-fortified milk distribution program on anemia and iron deficiency in low-income young children in Mexico. Am J Clin Nutr. 2010. 91(2):431–439.20016011 | Outcome
385 | Robert RC, Penny ME, Barbagelatta G, Gainer SA. Feeding Homemade Sugar Sweetened Beverages in Addition to Breastfeeding: Survey Results from Caregivers of Infants and Young Children in Peri-Urban Lima, Peru. Matern Child Health J. 2023. 27(12):2105–12.37209377 | Study design
386 | Robertson A, Parlesak A, Greiner T, Kent G, Cattaneo A. Biodiverse food solutions to enhance complementary feeding. Matern Child Nutr. 2016. 12(3):639–640.27350270 | Study design, Publication status
387 | Robinson SL, Sundaram R, Putnick DL, Predictors of Age at Juice Introduction and Associations with Subsequent Beverage Intake in Early and Middle Childhood. J Nutr. 2021. 151(11):3516–23.34486676 | Outcome
388 | Roche ML, Marquis GS, Gyorkos TW, Blouin B, Sarsoza J, Kuhnlein HV. A Community-Based Positive Deviance/Hearth Infant and Young Child Nutrition Intervention in Ecuador Improved Diet and Reduced Underweight. J Nutr Educ Behav. 2017. 49(3):196–203 e1.27843127 | Intervention/exposure
389 | Rodd C, Feely A, Becker AB, World Health Organization growth standards: How do Canadian children measure up?. Paediatrics and Child Health (Canada). 2021. 26(5):E208–E214. | Intervention/exposure, Outcome
390 | Rodriguez-Cano AM, Mier-Cabrera J, Allegre-Davalos AL, Munoz-Manrique C, Perichart-Perera O. Higher fat mass and fat mass accretion during the first six months of life in exclusively breastfed infants. Pediatr Res. 2020. 87(3):588–594.31434104 | Study design
391 | Rodriguez-Cano AM, Mier-Cabrera J, Munoz-Manrique C, Cardona-Perez A, Villalobos-Alcazar G, Perichart-Perera O. Anthropometric and clinical correlates of fat mass in healthy term infants at 6 months of age. BMC Pediatr. 2019. 19(1):60.30777039 | Study design, Intervention/exposure
392 | Rodriguez-Cano AM, Mier-Cabrera J, Rodriguez-Hernandez C, Allegre-Davalos AL, Munoz-Manrique C, Perichart-Perera O. Complementary feeding practices and their association with adiposity indicators at 12 months of age. J Dev Orig Health Dis. 2021. 12(5):780–787.33222718 | Intervention/exposure
393 | Rogers I, Emmett P, Gunnell D, Dunger D, Holly J. Milk as a food for growth? The insulin-like growth factors link. Public Health Nutr. 2006. 9(3):359–68.16684388 | Age at intervention/exposure
394 | Rogers S, Ramsay M, Blissett J. The Montreal Children's Hospital Feeding Scale: Relationships with parental report of child eating behaviours and observed feeding interactions. Appetite. 2018. 125:201–209.29428545 | Intervention/exposure, Outcome
395 | Rogers SL, Blissett J. Breastfeeding duration and its relation to weight gain, eating behaviours and positive maternal feeding practices in infancy. Appetite. 2017. 108:399–406.27756634 | Intervention/exposure, Outcome
396 | Rohde JF, Larsen SC, /1=A"/ngquist L, Effects of the Healthy Start randomized intervention on dietary intake among obesity-prone normal-weight children. Public Health Nutr. 2017. 20(16):2988 2997.28879820 | Age at intervention/exposure
397 | Rolland-Cachera MF. Breast feeding and growth trajectories: importance of the time frame of observation. Pediatr Res. 2020. 87(3):436–437.31683274 | Study design
398 | Rolland-Cachera MF, Deheeger M, Akrout M, Bellisle F. Influence of macronutrients on adiposity development: a follow up study of nutrition and growth from 10 months to 8 years of age. Int J Obes Relat Metab Disord. 1995. 19(8):573–8.7489029 | Intervention/exposure
399 | Rolland-Cachera MF, Deheeger M, P/1=e'/quignot F, Guilloud-Bataille M, Vinit F, Bellisle F. Adiposity and food intake in young children: the environmental challenge to individual susceptibility. Br Med J (Clin Res Ed). 1988. 296(6628):1037–8. | Intervention/exposure, Age at intervention/exposure
400 | Rollins BY, Francis LA. Off the Charts: Identifying and Visualizing Body Mass Index Trajectories of Rural, Poor Youth. J Pediatr. 2021.228:147–154 e2.32898580 | Intervention/exposure
401 | Rose CM, Birch LL, Savage JS. Dietary patterns in infancy are associated with child diet and weight outcomes at 6 years. Int J Obes (Lond). 2017. 41(5):783–788.28133360 | Intervention/exposure
402 | Rose CM, Savage JS, Birch LL. Patterns of early dietary exposures have implications for maternal and child weight outcomes. Obesity. 2016. 24(2):430–438.26717908 | Duplicate data
403 | Rosenstock S, Ingalls A, Foy Cuddy R, Effect of a Home-Visiting Intervention to Reduce Early Childhood Obesity Among Native American Children: A Randomized Clinical Trial. JAMA Pediatr. 2021. 175(2):133–142.33165594 | Intervention/exposure
404 | Ruottinen S, Niinikoski H, Lagstr/1=o"/m H, High sucrose intake is associated with poor quality of diet and growth between 13 months and 9 years of age: the special Turku Coronary Risk Factor Intervention Project. Pediatrics. 2008. 121(6):e1676–85.18519471 | Intervention/exposure
405 | Rush E, Paterson J, Obolonkin V. Food frequency information-relationships to body composition and apparent growth in 4-year-old children in the Pacific Island Family Study. N Z Med J. 2008. 121(1281):63–71. | Age at intervention/exposure
406 | Russo MD, Ahrens W, De Henauw S, The impact of adding sugars to milk and fruit on adiposity and diet quality in children: A cross-sectional and longitudinal analysis of the identification and prevention of dietary-and lifestyle-induced health effects in children and infants (IDEFICS) study. Nutrients. 2018. 10(10): 1350.30248889 | Age at intervention/exposure
407 | Rybak TM, Goetz AR, Stark LJ. Examining patterns of postnatal feeding in relation to infant's weight during the first year. Appetite. 2021. 166:105473.34153422 | Intervention/exposure
408 | Rzehak P, Oddy WH, Mearin ML, Infant feeding and growth trajectory patterns in childhood and body composition in young adulthood. Am J Clin Nutr. 2017. 106(2):568–580.28659295 | Intervention/exposure
409 | Saelens BE, Couch SC, Wosje KS, Stark LJ, Daniels SR. Relations among milk and non-milk beverage consumption, calcium, and relative weight in high-weight status children. J Clin Psychol Med Settings. 2006. 13(2): 117–125. | Age at intervention/exposure
410 | Salahuddin M, Perez A, Ranjit N, Hoelscher DM, Kelder SH. The associations of large-forgestational-age and infant feeding practices with children's body mass index z-score trajectories: the Early Childhood Longitudinal Study, Birth Cohort. Clin Obes. 2017. 7(5):307–315.28707388 | Intervention/exposure
411 | Saldanha-Gomes C, Hallimat Cissé A, Descarpentrie A, Prospective associations between dietary patterns, screen and outdoor play times at 2 years and age at adiposity rebound: The EDEN mother-child cohort. Preventive Medicine Reports. 2022. 25:101666. doi:10.1016/j.pmedr.2021.101666.35127350 | Age at intervention/exposure
412 | Salvo D, Ranjit N, Nielsen A, Akhavan N, van den Berg A. Characterizing Micro-scale Disparities in Childhood Obesity: Examining the Influence of Multilevel Factors on 4-Year Changes in BMI, Healthy Eating, and Physical Activity, Among a Cohort of Children Residing in Disadvantaged Urban Enclaves. Front Public Health. 2019. 7:301.31750284 | Age at intervention/exposure
413 | Samano R, Chico-Barba G, Martinez-Rojano H, Factors Associated With Weight, Length, and BMI Change in Adolescents' Offspring in Their First Year of Life. Front Pediatr. 2021. 9:709933.34532303 | Intervention/exposure
414 | Sanchez-Escobedo S, Azcorra H, Bogin B, Birth weight, birth order, and age at first solid food introduction influence child growth and body composition in 6- to 8-year-old Maya children: The importance of the first 1000 days of life. Am J Hum Biol. 2020. 32(5):e23385.31994809 | Study design
415 | Sanchez-Siles LM, Bernal MJ, Gil D, Are Sugar-Reduced and Whole Grain Infant Cereals Sensorially Accepted at Weaning? A Randomized Controlled Cross-Over Trial. Nutrients. 2020. 12(6):1883.32599738 | Intervention/exposure, Outcome
416 | Sanders TAB, Purves R. An anthropometric and dietary assessment of the nutritional status of vegan preschool children. J Hum Nutr. 1981. 35(5):349–357.7288184 | Age at intervention/exposure
417 | Sangalli CN, Leffa PS, Valmorbida JL, Lumey LH, Vitolo MR. Impact of promoting healthy infant feeding practices on energy intake and anthropometric measures of children up to 6 years of age: A randomised controlled trial. J Hum Nutr Diet. 2021. 34(5):771–783.34034359 | Intervention/exposure
418 | Santos LP, Assuncao MCF, Matijasevich A, Santos IS, Barros AJD. Dietary intake patterns of children aged 6 years and their association with socioeconomic and demographic characteristics, early feeding practices and body mass index. BMC Public Health. 2016. 16(1):1055.27716197 | Intervention/exposure, Age at intervention/exposure, Outcome
419 | Santos LP, Ong KK, Santos IS, Matijasevich A, Barros AJD. Effects of dietary intake patterns from 1 to 4 years on BMI z-score and body shape at age of 6 years: a prospective birth cohort study from Brazil. Eur J Nutr. 2019. 58(4):1723–1734.29774385 | Country
420 | Sasongko EPS, Ariyanto EF, Indraswari N, Rachmi CN, Alisjahbana A. Determinants of adolescent shortness in Tanjungsari, West Java, Indonesia. Asia Pac J Clin Nutr. 2019. 28(Suppl 1):S43–S50.30729774 | Country
421 | Sata M, Yamagishi K, Sairenchi T, Breastfeeding in Infancy in Relation to Subsequent Physical Size: A 20-year Follow-up of the Ibaraki Children's Cohort Study (IBACHIL). Journal of epidemiology. 2023. 33(2):63. doi:10.2188/jea.JE20200562.34744093 | Intervention/exposure
422 | Sauder KA, Kaar JL, Starling AP, Ringham BM, Glueck DH, Dabelea D. Predictors of Infant Body Composition at 5 Months of Age: The Healthy Start Study. J Pediatr. 2017. 183:94–99 e1.28161200 | Study design, Intervention/exposure
423 | Saure C, Armeno M, Barcala C, Giudici V, Mazza CS. Excessive weight gain in exclusively breastfed infants. J Pediatr Endocrinol Metab. 2017. 30(7):719–724.28593913 | Study design, Intervention/exposure
424 | Savage JS, Birch LL, Marini M, Anzman-Frasca S, Paul IM. Effect of the INSIGHT Responsive Parenting Intervention on Rapid Infant Weight Gain and Overweight Status at Age 1 Year: A Randomized Clinical Trial. JAMA Pediatr. 2016. 170(8):742–9.27271455 | Intervention/exposure
425 | Sazawal S, Dhingra U, Dhingra P, Micronutrient fortified milk improves iron status, anemia and growth among children 1-4 years: a double masked, randomized, controlled trial. PLoS One. 2010. 5(8):e12167.20730057 | Country
426 | Scharf RJ, Demmer RT, DeBoer MD. Longitudinal evaluation of milk type consumed and weight status in preschoolers. Arch Dis Child. 2013. 98(5):335–340.23508869 | Age at intervention/exposure
427 | Schneider BC, Gatica-Dominguez G, Assuncao MCF, Introduction to complementary feeding in the first year of life and risk of overweight at 24 months of age: changes from 2004 to 2015 Pelotas (Brazil) Birth Cohorts. Br J Nutr. 2020. 124(6):620–630.32381141 | Intervention/exposure
428 | Schneider-Worthington CR, Berger PK, Goran MI, Salvy SJ. Learning to overeat in infancy: Concurrent and prospective relationships between maternal BMI, feeding practices and child eating response among Hispanic mothers and children. Pediatr Obes. 2021. 16(6):e12756.33225624 | Intervention/exposure, Outcome
429 | Scully H, Alberdi G, Segurado R, Child Care Exposure Influences Childhood Adiposity at 2 Years: Analysis from the ROLO Study. Child Obes. 2017. 13(2):93–101.27854513 | Study design
430 | See VHL, Mori TA, Prescott SL, Beilin LJ, Burrows S, Huang RC. Cardiometabolic risk factors at 5 years after omega-3 fatty acid supplementation in infancy. Pediatrics. 2018. 142(1):e20162623.29884682 | Intervention/exposure
431 | Sekhobo JP. Estimation of WIC effects in multilevel, cross-sector obesity prevention interventions. Obesity. 2017. 25(7):1157–1158.28653503 | Study design
432 | Seyyedi N, Rahimi B, Eslamlou HRF, Afshar HL, Spreco A, Timpka T. Smartphone-Based Maternal Education for the Complementary Feeding of Undernourished Children Under 3 Years of Age in Food-Secure Communities: Randomised Controlled Trial in Urmia, Iran. Nutrients. 2020. 12(2):587.32102310 | Intervention/exposure, Age at intervention/exposure, Health status
433 | Shashaj B, Graziani MP, Contoli B, Energy Balance–Related Behaviors, Perinatal, Sociodemographic, and Parental Risk Factors Associated with Obesity in Italian Preschoolers. J Am Coll Nutr. 2016. 35(4):362–371.26933953 | Study design, Age at intervention/exposure
434 | Shashaj B, Contoli B, Raponi M, Energy Balance-Related Behaviors, Perinatal, Sociodemographic, and Parental Risk Factors Associated with Obesity in Italian Preschoolers. J Am Coll Nutr. 2016. 35(4):362–371.26933953 | Age at intervention/exposure
435 | Shefferly A, Scharf RJ, Deboer MD. Longitudinal evaluation of 100% fruit juice consumption on BMI status in 2-5-year-old children. Pediatr Obes. 2016. 11(3):221–227.26110996 | Age at intervention/exposure
436 | Shin KO, Oh SY, Park HS. Empirically derived major dietary patterns and their associations with overweight in Korean preschool children. Br J Nutr. 2007. 98(2):416–21.17433127 | Age at intervention/exposure
437 | Shinn LM, Tangney CC, Busche C, Sharp CM, Mullen MC. Demographic Correlates of Infant Feeding Practices and Growth Performance in the First Year of Life. Int J Pediatr. 2018. 2018:6569204.30364029 | Intervention/exposure
438 | Simoneau G, Moodie EEM, Platt RW, Chakraborty B. Non-regular inference for dynamic weighted ordinary least squares: understanding the impact of solid food intake in infancy on childhood weight. Biostatistics. 2018. 19(2):233–246.28968752 | Study design, Country
439 | Simpson RJ, Diedericks I, Haresign H. Evaluation of the first 3 years of Nutri-eSTEP usage (2013-2016). Canadian Journal of Dietetic Practice & Research. 2018. 79(3):150–150. | Publication status
440 | Singhal A. The Impact of Human Milk Feeding on Long-Term Risk of Obesity and Cardiovascular Disease. Breastfeed Med. 2019. 14(S1):S9–S10.30985205 | Study design
441 | Sirkka O, Hof MH, Vrijkotte T, Feeding patterns and BMI trajectories during infancy: a multiethnic, prospective birth cohort. BMC Pediatr. 2021. 21(1):34.33441111 | Intervention/exposure
442 | Sirkka O, Vrijkotte T, Halberstadt J, Prospective associations of age at complementary feeding and exclusive breastfeeding duration with body mass index at 5-6 years within different risk groups. Pediatr Obes. 2018. 13(8):522–529.29695025 | Intervention/exposure
443 | Sirkka O, Vrijkotte T, Houtum LV, Infant Feeding and Ethnic Differences in Body Mass Index during Childhood: A Prospective Study. Nutrients. 2021. 13(7):2291.34371801 | Intervention/exposure
444 | Siziba LP, Baumgartner J, Ricci C, Associations of plasma total phospholipid fatty acid patterns with feeding practices, growth, and psychomotor development in 6-month-old South African infants. Matern Child Nutr. 2019. 15(3):e12763.30489019 | Study design, Country
445 | Skinner JD, Bounds W, Carruth BR, Ziegler P. Longitudinal calcium intake is negatively related to children's body fat indexes. J Am Diet Assoc. 2003. 103(12):1626–31.14647089 | Age at intervention/exposure
446 | Smith-Brown P, Morrison M, Krause L, Davies PSW. Microbiota and Body Composition During the Period of Complementary Feeding. J Pediatr Gastroenterol Nutr. 2019. 69(6):726–732.31568152 | Study design
447 | Smuts CM, Matsungo TM, Malan L, Effect of small-quantity lipid-based nutrient supplements on growth, psychomotor development, iron status, and morbidity among 6- to 12-mo-old infants in South Africa: a randomized controlled trial. Am J Clin Nutr. 2019. 109(1):55–68.30649163 | Country
448 | Soares S, Santos AC, Peres FS, Barros H, Fraga S. Early life socioeconomic circumstances and cardiometabolic health in childhood: Evidence from the Generation XXI cohort. Prev Med. 2020. 133:106002.32007527 | Intervention/exposure
449 | Specht IO, Rohde JF, Olsen NJ, Heitmann BL. Duration of exclusive breastfeeding may be related to eating behaviour and dietary intake in obesity prone normal weight young children. PLoS One. 2018. 13(7):e0200388.29995949 | Intervention/exposure, Age at intervention/exposure
450 | Stearns JC, Zulyniak MA, de Souza RJ, Ethnic and diet-related differences in the healthy infant microbiome. Genome Med. 2017. 9(1):32.28356137 | Study design, Outcome
451 | Stroobant W, Braun KV, Kiefte-de Jong JC, Intake of Different Types of Fatty Acids in Infancy Is Not Associated with Growth, Adiposity, or Cardiometabolic Health up to 6 Years of Age. J Nutr. 2017. 147(3):413–420.28122928 | Intervention/exposure
452 | Strucińska M, Rowicka G. Dietary intake of vitamin D in obese children aged 1-3 years. Roczniki Państwowego Zakładu Higieny. 2015. 66(4):353–360.26656417 | Study design
453 | Sun C, Foskey RJ, Allen KJ, The Impact of Timing of Introduction of Solids on Infant Body Mass Index. J Pediatr. 2016. 179:104–110.e1.27663213 | Study design
454 | Susanto T, Syahrul, Sulistyorini L, Rondhianto, Yudisianto A. Local-food-based complementary feeding for the nutritional status of children ages 6-36 months in rural areas of Indonesia. Korean J Pediatr. 2017. 60(10):320–326.29158766 | Country
455 | Susatia B, Riswari RM. Green Bean Juice as Supplementary Food to Increase the Weight of Underweight Toddlers. Open Access Macedonian Journal of Medical Sciences. 2021. 9(G):297. doi:10.3889/oamjms.2021.7494. | Study design
456 | Svensson V, Sobko T, Ek A, Obesogenic dietary intake in families with 1-year-old infants at high and low obesity risk based on parental weight status: baseline data from a longitudinal intervention (Early STOPP). Eur J Nutr. 2016. 55(2):781–792.25893717 | Study design
457 | Switkowski KM, Jacques PF, Must A, Fleisch A, Oken E. Associations of protein intake in early childhood with body composition, height, and insulin-like growth factor i in mid-childhood and early adolescence. Am J Clin Nutr. 2019. 109(4):1154–1163.30869114 | Intervention/exposure, Age at intervention/exposure
458 | Syrad H, Llewellyn CH, van Jaarsveld CH, Johnson L, Jebb SA, Wardle J. Energy and nutrient intakes of young children in the UK: findings from the Gemini twin cohort. Br J Nutr. 2016. 115(10):1843–50.27093345 | Outcome
459 | Tahir MJ, Michels KB, Willett WC, Forman MR. Age at Introduction of Solid Food and Obesity Throughout the Life Course. Obesity (Silver Spring). 2018. 26(10):1611–1618.30204942 | Study design
460 | Talavera JO, Garcia-Vilchis MJ, Labrada-Alba TS, Olvera-Flores F, Martinez-Jaureguiberry MF, Salgado-Enriquez B. Moderate acute malnutrition prevention with a ready-to-use supplementary food in pre-school children from rural communities. Gac Med Mex. 2020. 156(6):499–508.33877118 | Age at intervention/exposure
461 | Tang M, Ma C, Weinheimer-Haus EM, Different gut microbiota in U.S. formula-fed infants consuming a meat vs. dairy-based complementary foods: A randomized controlled trial. Front Nutr. 2023. 9:1063518.36778973 | Duplicate data
462 | Tang M. The impact of complementary feeding foods of animal origin on growth and the risk of overweight in infants. Anim Front. 2019. 9(4):5–11.31667006 | Study design
463 | Taverno Ross SE, Barone Gibbs B, Documet PI, Pate RR. ANDALE Pittsburgh: results of a promotora-led, home-based intervention to promote a healthy weight in Latino preschool children. BMC Public Health. 2018. 18(1):360.29548321 | Age at intervention/exposure
464 | Tawia S, McGuire E. Early weight loss and weight gain in healthy, full-term, exclusively breastfed infants. Australian Midwifery News. 2016. 16(2):35–36. | Study design
465 | Taylor RW, Gray AR, Heath ALM, Sleep, nutrition, and physical activity interventions to prevent obesity in infancy: Follow-up of the Prevention of Overweight in Infancy (POI) randomized controlled trial at ages 3.5 and 5 y. Am J Clin Nutr. 2018. 108(2):228–236.30101329 | Intervention/exposure
466 | Taylor RW, Williams SM, Fangupo LJ, Effect of a Baby-Led Approach to Complementary Feeding on Infant Growth and Overweight: A Randomized Clinical Trial. JAMA Pediatr. 2017. 171(9):838–846.28692728 | Intervention/exposure
467 | Tctr . Nutrition Education Intervention to Improve Child Feeding Practice and Nutritional Status of Children Age 6-23 Months in Indonesia. http://www.who.int/trialsearch/Trial2.aspx?TrialID=TCTR20200213003. 2020. | Publication status
468 | Temples HS, Willoughby D, Holaday B, Breastfeeding and Growth of Children in the Peri/postnatal Epigenetic Twins Study (PETS): Theoretical Epigenetic Mechanisms. J Hum Lact. 2016. 32(3):481–8.27009979 | Study design, Intervention/exposure
469 | Thaweekul P, Sinlapamongkolkul P, Tonglim J, Sritipsukho P. Associations between the infant and young child feeding index and nutritional status. Pediatr Int. 2021. 63(8):958–964.33289190 | Study design
470 | Thompson AL, Wasser H, Nulty A, Bentley ME. Feeding style profiles are associated with maternal and infant characteristics and infant feeding practices and weight outcomes in African American mothers and infants. Appetite. 2021. 160:105084.33359466 | Intervention/exposure
471 | Thomson JL, Goodman MH, Tussing-Humphreys LM, Landry AS. Infant growth outcomes from birth to 12 months of age: findings from the Delta Healthy Sprouts randomized comparative impact trial. Obesity Science and Practice. 2018. 4(4):299–307.30151225 | Intervention/exposure
472 | Thorisdottir B, Gunnarsdottir I, Palsson GI, Halldorsson TI, Thorsdottir I. Animal protein intake at 12 months is associated with growth factors at the age of six. Acta Paediatr. 2014. 103(5):512–7.24471761 | Intervention/exposure
473 | Tian Q, Gao X, Sha T, Effect of feeding patterns on growth and nutritional status of children aged 0-24 months: A Chinese cohort study. PLoS One. 2019. 14(11):e0224968.31743354 | Intervention/exposure
474 | Ţincu, IF, Păcurar D, Ţincu RC, Becheanu C. Influence of Protein Intake during Complementary Feeding on Body Size and IGF-I Levels in Twelve-month-old Infants. Balkan Med J. 2020. 37(1):54–55. | Study design
475 | Trabulsi JC, Smethers AD, Eosso JR, Papas MA, Stallings VA, Mennella JA. Impact of early rapid weight gain on odds for overweight at one year differs between breastfed and formula-fed infants. Pediatr Obes. 2020. 15(10):e12688.32705816 | Intervention/exposure
476 | Trier C, Fonvig CE, Bøjsøe C, No influence of sugar, snacks and fast food intake on the degree of obesity or treatment effect in childhood obesity. Pediatr Obes. 2016. 11(6):506–512.26909660 | Age at intervention/exposure
477 | Ua-Areechit T, Suteerojntrakool O, Pongcharoen T, Breastfeeding duration is associated with higher adiposity at 6-8 months of age. Matern Child Nutr. 2023. 19(1):e13438.36254499 | Study design
478 | Usheva N, Galcheva S, Cardon G, Complementary Feeding and Overweight in European Preschoolers: The ToyBox-Study. Nutrients. 2021. 13(4):1199.33916419 | Study design
479 | Vadiveloo M, Tovar A, Ostbye T, Benjamin-Neelon SE. Associations between timing and quality of solid food introduction with infant weight-for-length z-scores at 12 months: Findings from the Nurture cohort. Appetite. 2019. 141:104299.31132424 | Intervention/exposure
480 | Vafa M, Heshmati J, Sadeghi H, Is exclusive breastfeeding and its duration related to cardio respiratory fitness in childhood?. Journal of Maternal-Fetal and Neonatal Medicine. 2016. 29(3):461–465.25655530 | Intervention/exposure, Outcome
481 | van Beijsterveldt I, de Fluiter KS, Breij LM, van der Steen M, Hokken-Koelega ACS. Fat mass and fat-free mass track from infancy to childhood: New insights in body composition programming in early life. Obesity (Silver Spring). 2021. 29(11):1899–906.34549538 | Intervention/exposure
482 | van der Veek SMC, de Graaf C, de Vries JHM, Baby's first bites: a randomized controlled trial to assess the effects of vegetable-exposure and sensitive feeding on vegetable acceptance, eating behavior and weight gain in infants and toddlers. BMC Pediatr. 2019. 19(1):266.31370830 | Study design, Outcome
483 | van Gijssel RM, Braun KV, Kiefte-de Jong JC, Jaddoe VW, Franco OH, Voortman T. Associations between Dietary Fiber Intake in Infancy and Cardiometabolic Health at School Age: The Generation R Study. Nutrients. 2016. 8(9):531.27589791 | Intervention/exposure
484 | van Gijssel RMA, Braun KVE, Kiefte-de Jong JC, Jaddoe VWV, Franco OH, Voortman T. Associations between dietary fiber intake in infancy and cardiometabolic health at school age: The generation R study. Nutrients. 2016. 8(9):531.27589791 | Intervention/exposure
485 | van Staveren WA, Dhuyvetter JH, Bons A, Zeelen M, Hautvast JG. Food consumption and height/weight status of Dutch preschool children on alternative diets. J Am Diet Assoc. 1985. 85(12):1579–84.4067152 | Intervention/exposure
486 | van Vliet MS, Schultink JM, Jager G, The Baby's First Bites RCT: Evaluating a Vegetable-Exposure and a Sensitive-Feeding Intervention in Terms of Child Health Outcomes and Maternal Feeding Behavior During Toddlerhood. J Nutr. 2022. 152(2):386–98.34791320 | Intervention/exposure
487 | Vandenplas Y, Dupont C, Eigenmann P, Growth in Infants with Cow's Milk Protein Allergy Fed an Amino Acid-Based Formula. Pediatr Gastroenterol Hepatol Nutr. 2021. 24(4):392–402.34316474 | Study design, Intervention/exposure
488 | Vanderhout SM, Keown-Stoneman CDG, Birken CS, Connor DL, Thorpe KE, Maguire JL. Cow’s milk fat and child adiposity: a prospective cohort study. Int J Obes. 2021. 45(12):2623–2628. | Age at intervention/exposure
489 | Vandyousefi S, Whaley SE, Widen EM, Association of breastfeeding and early exposure to sugar-sweetened beverages with obesity prevalence in offspring born to mothers with and without gestational diabetes mellitus. Pediatr Obes. 2019. 14(12):e12569.31389196 | Study design
490 | Vard B, Adham A, Riahi R, Association of early life factors with dyslipidemia in children and adolescents: The CASPIAN-V study. Health Promot Perspect. 2020. 10(4):349–358.33312930 | Study design
491 | Vehapoglu A, Goknar N, Turel O, Torun E, Ozgurhan G. Risk factors for childhood obesity: Do the birth weight, type of delivery, and mother's overweight have an implication on current weight status?. World J Pediatr. 2017. 13(5):457–464.28434072 | Study design
492 | Ventura AK, Li R, Xu X. Associations between Bottle-Feeding during Infancy and Obesity at Age 6 Years Are Mediated by Greater Infancy Weight Gain. Child Obes. 2020. 16(5):316. doi:10.1089/chi.2019.0299.32498550 | Intervention/exposure
493 | Ventura AK, Whaley SE. Strategies to promote responsive bottle-feeding in WIC predict less frequent use of food to soothe and healthier weight status for infants with negative temperaments. Pediatr Obes. 2022. 17(8):e12908. doi:10.1111/ijpo.12908.35224881 | Intervention/exposure
494 | Ventura AK. Developmental Trajectories of Bottle-Feeding During Infancy and Their Association with Weight Gain. J Dev Behav Pediatr. 2017. 38(2):109–119.27941411 | Intervention/exposure, Outcome
495 | Verbestel V, De Coen V, Van Winckel M, Huybrechts I, Maes L, De Bourdeaudhuij I. Prevention of overweight in children younger than 2 years old: a pilot cluster-randomized controlled trial. Public Health Nutr. 2014. 17(6):1384–1392.23701835 | Intervention/exposure
496 | Viner RM, Costa S, Johnson W. Patterns of BMI development between 10 and 42 years of age and their determinants in the 1970 British Cohort Study. J Epidemiol Community Health. 2019. 73(1):79–85.30409921 | Intervention/exposure
497 | Virudachalam S, Gruver RS, Gerdes M, Mothers' and clinicians' priorities for obesity prevention among black, high-risk infants. Am J Prev Med. 2016. 51(1):46–53.26947214 | Study design, Intervention/exposure
498 | Visioli F, Poli A. Limitations in study of sugar-sweetened beverages. J Am Diet Assoc. 2008. 108(1):34–35. | Study design
499 | Vlasblom E, van Grieken A, Beltman M, L’Hoir MP, Raat H, Boere-Boonekamp MM. Parenting support to prevent overweight during regular well-child visits in 0-3 year old children (BBOFT+ program), a cluster randomized trial on the effectiveness on child BMI and health behaviors and parenting. PLoS One. 2020. 15(8):e0237564.32810194 | Intervention/exposure
500 | Vobecky JS, Vobecky J, Shapcott D, Demers PP. Nutrient intake patterns and nutritional status with regard to relative weight in early infancy. Am J Clin Nutr. 1983. 38(5):730–738.6637865 | Intervention/exposure
501 | Vogelezang S, Santos S, van der Beek EM, Infant breastfeeding and childhood general, visceral, liver, and pericardial fat measures assessed by magnetic resonance imaging. Am J Clin Nutr. 2018. 108(4):722–729.30107466 | Intervention/exposure
502 | Voortman T, Braun KVE, Kiefte-De Jong JC, Jaddoe VWV, Franco OH, Van Den Hooven EH. Protein intake in early childhood and body composition at the age of 6 years: The Generation R Study. Int J Obes. 2016. 40(6):1018–1025. | Intervention/exposure
503 | Voortman T, Leermakers ET, Franco OH, A priori and a posteriori dietary patterns at the age of 1 year and body composition at the age of 6 years: the Generation R Study. Eur J Epidemiol. 2016. 31(8):775–83.27384175 | Intervention/exposure
504 | Voortman T, Leermakers ETM, Franco OH, A priori and a posteriori dietary patterns at the age of 1 year and body composition at the age of 6 years: the Generation R Study. Eur J Epidemiol. 2016. 31(8):775–783.27384175 | Intervention/exposure
505 | Voortman T, van den Hooven EH, Tielemans MJ, Protein intake in early childhood and cardiometabolic health at school age: the Generation R Study. Eur J Nutr. 2016. 55(6):2117–2127.26329684 | Intervention/exposure
506 | Voortman T, van den Hooven E, Tielemans M, Protein intake in early childhood and cardiometabolic health at school age: the Generation R Study. Eur J Nutr. 2016. 55(6):2117–2127.26329684 | Intervention/exposure
507 | Wallenborn JT, Levine GA, Carreira Dos Santos A, Grisi S, Brentani A, Fink G. Breastfeeding, Physical Growth, and Cognitive Development. Pediatrics. 2021. 147(5):e2020008029.33888567 | Intervention/exposure
508 | Wang CA, Attia JR, Lye SJ, The interactions between genetics and early childhood nutrition influence adult cardiometabolic risk factors. Sci Rep. 2021. 11(1):14826.34290306 | Intervention/exposure
509 | Wang J, Chang S, Zhao L, Effectiveness of community-based complementary food supplement (Yingyangbao) distribution in children aged 6-23 months in poor areas in China. PLoS One. 2017. 12(3):e0174302.28319154 | Study design, Intervention/exposure
510 | Wang L, van Grieken A, Yang-Huang J, Relationship between socioeconomic status and weight gain during infancy: The BeeBOFT study. PLoS One. 2018. 13(11):e0205734.30388128 | Study design, Intervention/exposure
511 | Wang P, Hao M, Han W, Yamauchi T. Factors associated with nutritional status and motor development among young children. Nurs Health Sci. 2019. 21(3):323–329.30989749 | Study design
512 | Waters WF, Gallegos CA, Karp C, Lutter C, Stewart C, Iannotti L. Cracking the Egg Potential: Traditional Knowledge, Attitudes, and Practices in a Food-Based Nutrition Intervention in Highland Ecuador. Food Nutr Bull. 2018. 39(2):206–218.29558837 | Study design, Outcome
513 | Wee PH, Loy SL, Toh JY, Circadian feeding patterns of 12-month-old infants. Br J Nutr. 2017. 117(12):1702–1710.28789728 | Study design, Intervention/exposure
514 | Weker H, Brudnicka E, Barańska M, Dietary Patterns of Children Aged 1-3 Years in Poland in Two Population Studies. Ann Nutr Metab. 2019. 75(1):66–76.31266006 | Study design, Intervention/exposure
515 | Welsh JA, Cogswell ME, Rogers S, Rockett H, Mei Z, Grummer-Strawn LM. Overweight among low-income preschool children associated with the consumption of sweet drinks: Missouri, 1999-2002. Pediatrics. 2005. 115(2):e223–9.15687430 | Age at intervention/exposure
516 | Wen LM, Baur LA, Simpson JM, Rissel C, Wardle K, Flood VM. Effectiveness of home based early intervention on children's BMI at age 2: Randomised controlled trial. BMJ (Online). 2012. 344(7865):e3732. | Intervention/exposure
517 | Whaley SE, Koleilat M, Leonard S, Whaley M. Breastfeeding Is Associated With Reduced Obesity in Hispanic 2- to 5-Year-Olds Served by WIC. J Nutr Educ Behav. 2017. 49(7 Suppl 2):S144–S150 e1.28689551 | Intervention/exposure
518 | Wojcicki JM, Heyman MB, Elwan D, Lin J, Blackburn E, Epel E. Early exclusive breastfeeding is associated with longer telomeres in Latino preschool children. Am J Clin Nutr. 2016. 104(2):397–405.27440083 | Outcome
519 | Wojcicki JM, Young MB, Perham-Hester KA, e Schweinitz P, Gessner BD. Risk factors for obesity at age 3 in Alaskan children, including the role of beverage consumption: results from Alaska PRAMS 2005-2006 and its three-year follow-up survey, CUBS, 2008-2009. PLoS One. 2015. 10(3):e0118711.25793411 | Age at intervention/exposure
520 | Wood CT, Witt WP, Skinner AC, Effects of Breastfeeding, Formula Feeding, and Complementary Feeding on Rapid Weight Gain in the First Year of Life. Acad Pediatr. 2021. 21(2):288–296.32961335 | Intervention/exposure
521 | Wright M, Mendez MA, Sotres-Alvarez D, Adair L. Breastfeeding and Protein Intake Influence Body Mass Index from 2 Months to 22 Years in the Cebu Longitudinal Health and Nutrition Survey. J Nutr. 2016. 146(10):2085–2092.27581582 | Intervention/exposure, Country
522 | Wright M, Mendez MA, Sotres-Alvarez D, Adair L. Breastfeeding and protein intake influence body mass index from 2 Months to 22 years in the Cebu Longitudinal Health and Nutrition Survey. J Nutr. 2016. 146(10):2085–2092.27581582 | Country
523 | Wright M, Sotres-Alvarez D, Mendez MA, Adair L. The association of trajectories of protein intake and age-specific protein intakes from 2 to 22 years with BMI in early adulthood. Br J Nutr. 2017. 117(5):750–758.28347359 | Country
524 | Wright MJ, Mendez MA, Bentley ME, Adair LS. Breastfeeding modifies the impact of diarrhoeal disease on relative weight: a longitudinal analysis of 2-12 month-old Filipino infants. Matern Child Nutr. 2017. 13(2):e12312.27062326 | Country
525 | Xu H, Du S, Liu A, Zhang Q, Ma G. Low Dietary Diversity for Recommended Food Groups Increases the Risk of Obesity among Children: Evidence from a Chinese Longitudinal Study. Nutrients. 2022. 14(19):4068.36235720 | Age at intervention/exposure
526 | Yang S, Mei H, Mei H, Risks of maternal prepregnancy overweight/obesity, excessive gestational weight gain, and bottle-feeding in infancy rapid weight gain: evidence from a cohort study in China. Sci China Life Sci. 2019. 62(12):1580–1589.31745693 | Intervention/exposure
527 | Yao S, Xiao S, Jin X, Effect of a community-based child health counselling intervention on health-seeking behaviours, complementary feeding and nutritional condition among children aged 6-23 months in rural China: A pre- and post-comparison study. Matern Child Nutr. 2022. 18(1):e13289.34816596 | Study design, Intervention/exposure
528 | Yeung H, Leff M, Rhee KE. Effect of Exclusive Breastfeeding Among Overweight and Obese Mothers on Infant Weight-for-Length Percentile at 1 Year. Breastfeed Med. 2017. 12:39–47.27834508 | Intervention/exposure
529 | Yuan M, Lu M, Guo Y, Timing of infant formula introduction in relation to BMI and overweight at ages 1 and 3 years: the Born in Guangzhou Cohort Study (BIGCS). Br J Nutr. 2023. 129(1):166. doi:10.1017/S000711452200071X.35264258 | Intervention/exposure
530 | Zaragoza Cortes J, Trejo Osti LE, Ocampo Torres M, Maldonado Vargas L, Ortiz Gress AA. Poor breastfeeding, complementary feeding and dietary diversity in children and their relationship with stunting in rural communities. Nutr Hosp. 2018. 35(2):271–278.29756958 | Study design
531 | Zaragoza Cortes J, Trejo Osti LE, Ocampo Torres M. Impact of a complementary feeding intervention and mother's perceptions of child weight status in infants. Nutr Hosp. 2019. 36(2):282–289.30868904 | Intervention/exposure
532 | Zavareh MSA, Hasani M, Darabi M, Growth indicators and nutritional supplement evaluation in 6-12 months year old children’s: A perspective from Ilam. Electron J Gen Med. 2018. 15(3):em17. | Study design
533 | Zhang Y, Wu Q, Wang W, Effectiveness of complementary food supplements and dietary counselling on anaemia and stunting in children aged 6-23 months in poor areas of Qinghai Province, China: a controlled interventional study. BMJ Open. 2016. 6(10):e011234. | Intervention/exposure
534 | Zheng M, Hesketh KD, Vuillermin P, Determinants of rapid infant weight gain: A pooled analysis of seven cohorts. Pediatr Obes. 2022. 17(10):e12928.35510714 | Intervention/exposure
535 | Zheng M, Cameron AJ, Birken CS, Early Infant Feeding and BMI Trajectories in the First 5 Years of Life. Obesity (Silver Spring). 2020. 28(2):339–346.31970916 | Intervention/exposure
536 | Zheng M, Campbell KJ, Baur L, Rissel C, Wen LM. Infant feeding and growth trajectories in early childhood: the application and comparison of two longitudinal modelling approaches. Int J Obes (Lond). 2021. 45(10):2230–2237.34230577 | Intervention/exposure
537 | Zheng M, Hesketh KD, McNaughton SA, Quantifying the overall impact of an early childhood multi-behavioural lifestyle intervention. Pediatr Obes. 2022. 17(3):12861. | Intervention/exposure
538 | Zheng M, Lioret S, Hesketh KD, Spence A, Taylor R, Campbell KJ. Association Between Longitudinal Trajectories of Lifestyle Pattern and BMI in Early Childhood. Obesity. 2021. 29(5):879–887.33899335 | Intervention/exposure
539 | Zheng M, Yu HJ, He QQ, Protein Intake During Infancy and Subsequent Body Mass Index in Early Childhood: Results from the Melbourne InFANT Program. J Acad Nutr Diet. 2021. 121(9):1775–1784.33839065 | Intervention/exposure
540 | Ziesmann A, Kiflen R, de Rubeis V, The association between early childhood and later childhood sugar-containing beverage intake: A prospective cohort study. Nutrients. 2019. 11(10):2338.31581586 | Age at intervention/exposure, Outcome