# Appendix 4 Literature search strategy

## Searches from existing reviews

The search conducted for an existing review identified articles published between January 1980 and July 2016. This 1 search was used in 2 systematic reviews, listed below. Both of those reviews were used in this review. For the complete search documentation, refer to:

English LK, Obbagy JE, Wong YP, ., Timing of Introduction of Complementary Foods and Beverages and Growth, Size, and Body Composition: A Systematic Review. April 2019. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: 10.52570/NESR.PB242018.SR0305.

English LK, Obbagy JE, Wong YP, ., Types and Amounts of Complementary Foods and Beverages and Growth, Size, and Body Composition: A Systematic Review. April 2019. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: 10.52570/NESR.PB242018.SR0306.

## Search A

This search was conducted to update the search from the existing review (referenced above). This search was first run on October 27, 2021, and then periodically run using NESR’s continuous evidence monitoring methods through May 2023. *

* USDA Nutrition Evidence Systematic Review Branch. Chapter 10: Continuous Evidence Monitoring. In: USDA Nutrition Evidence Systematic Review: Methodology Manual. February 2023. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: https://nesr.usda.gov/methodology-overview.

### Database: PubMed

Provider: U.S. National Library of Medicine

Date(s) Searched: October 27, 2021 (initial search); October 27, 2021 – June 1, 2023 (continuous evidence monitoring)

Dates Covered: July 20, 2016 - May 31, 2023

Table A 4 Search for PubMed (Search A)

Search # | Concept | String
#1 | Infant Feeding | “Infant Nutritional Physiological Phenomena”[Mesh] OR Complementary[tiab] OR supplementary[tiab] OR wean*[tiab] OR transition*[tiab] OR introduction[ti] OR introducing[tiab] OR introduced[tiab] OR “introduction of”[tiab] OR “introduction to”[tiab] OR “infant feed*”[tiab] OR “toddler feeding”[tiab] OR IYCF[tiab] OR “infant and young child feeding”[tiab]
#2 | Food and Beverage | “Diet”[MeSH] OR “Meals”[MeSH] OR “Food and Beverages”[Mesh] OR “Edible Grain”[Mesh] OR meal*[tiab] OR feeding*[tiab] OR food*[tiab] OR beverage*[tiab] OR eating[tiab] OR diet[tiab] OR diets[tiab] OR cereal*[tiab] OR bread*[tiab] OR whole grain*[tiab] OR juice*[tiab] OR milk[tiab] OR dairy[tiab] OR meat[tiab] OR cheese[tiab] OR yogurt[tiab] OR yoghurt*[tiab] OR fruit*[tiab] OR vegetable*[tiab] OR egg[tiab] OR eggs[tiab] OR nut[tiab] OR nuts[tiab] OR peas[tiab] OR beans[tiab] OR legume*[tiab] OR snack*[tiab] OR candy[tiab] OR “Fast Food*”[tiab] OR seeds[tiab] OR seafood[tiab] OR shellfish[tiab] OR fish[tiab] OR soymilk[tiab] OR wheat[tiab] OR “soy”[tiab] OR “soybean”[tiab]
#3 | Growth, body composition, and risk of obesity (pediatric) | “Adipose Tissue”[Mesh] OR “Body Composition”[Mesh] OR “Body Weights and Measures”[MeSH:NoExp] OR “Body Fat Distribution”[Mesh] OR “Body Mass Index”[Mesh] OR “Body Size”[Mesh] OR “Skinfold Thickness”[Mesh] OR “Waist-Hip Ratio”[Mesh] OR “Growth”[Mesh:NoExp] OR anthropometr*[tiab] OR body fat[tiab] OR fat mass[tiab] OR fat free mass[tiab] OR lean mass[tiab] OR obese[tiab] OR obesity[tiab] OR underweight[tiab] OR overweight[tiab] OR weight status[tiab] OR Crown-Rump Length*[tiab] OR body mass index[tiab] OR BMI[tiab] OR adipos*[tiab] OR birth weight*[tiab] OR body weight[tiab] OR body height[tiab] OR body size[tiab] OR body composition[tiab] OR overnutrition[tiab] OR wasting[tiab] OR healthy weight[tiab] OR skin fold[tiab] OR skin folds[tiab] OR skinfold[tiab] OR skinfolds[tiab] OR “Weight Gain”[MeSH] OR “Weight Loss”[MeSH:NoExp] OR weight gain[tiab] OR weight decreas*[tiab] OR (weight[tiab] AND (loss*[tiab] OR chang*[tiab] OR trajector*[tiab])) OR “Growth Charts”[Mesh] OR “growth and development" [Subheading] OR “Growth and Development”[MeSH:NoExp] OR growth[tiab] OR “Overnutrition”[Mesh] OR overeat*[tiab] OR “over eat”[tiab] OR overfed[tiab] OR overfeed*[tiab] OR “under-nutrition”[tiab] OR undernutrition[tiab] OR growth chart*[tiab] OR stunting[tiab] OR stunted[tiab] OR weight for height[tiab] OR stature for age[tiab] OR weight for age[tiab] OR height for age[tiab] OR length for age[tiab] OR weight for length[tiab] OR failure to thrive[tiab]
#4 | | #1 AND #2 AND #3
#5 | Limiters | #5 NOT ("Animals”[Mesh] NOT ("Animals”[Mesh] AND "Humans”[Mesh])); NOT (editorial[ptyp] OR comment[ptyp] OR commentary[tiab] OR news[ptyp] OR letter[ptyp] OR review[ptyp] OR systematic review[ptyp] OR systematic review[ti] OR meta-analysis[ptyp] OR meta-analysis[ti] OR meta-analyses[ti] OR protocol[ti] OR protocols[ti] OR retracted publication[ptyp] OR retraction of publication[ptyp] OR retraction of publication[tiab] OR retraction notice[ti] OR“retracted publication”[ti] OR “Congress”[Publication Type] OR “Consensus Development Conference”[Publication Type] OR “conference abstract*”[tiab] OR “conference proceeding*”[tiab] OR “conference paper*”[tiab] OR “practice guideline”[ptyp] OR “practice guideline”[ti]); Language: English; Publication Date: 07/20/2016 – 6/31/2023

### Database: Embase

Provider: Elsevier

Date(s) Searched: October 27, 2021 (initial search); October 27, 2021 – June 1, 2023 (continuous evidence monitoring)

Dates Covered: July 20, 2016 - May 31, 2023

Table A 5 Search for Embase (Search A)

Search # | Concept | String
#1 | Infant Feeding | ‘Infant Nutrition’/exp OR ‘complementary’:ab,ti OR ‘supplementary’:ab,ti OR ‘wean*’:ab,ti OR ‘transition*’:ab,ti OR ‘introduction’:ti OR ‘introducing’:ab,ti OR ‘introduced’:ab,ti OR ‘introduction of’:ab,ti OR ‘introduction to’:ab,ti OR ‘infant feed*’:ab,ti OR ‘toddler feeding’:ab,ti OR ‘IYCF’:ab,ti OR ‘infant and young child feeding’:ab,ti
#2 | Food and Beverage | ‘diet’/exp OR ‘meal’/exp OR ‘Food’/exp OR ‘Beverages’/exp OR ‘meal*’:ab,ti OR ‘feeding*’:ab,ti OR ‘food*’:ab,ti OR ‘beverage*’:ab,ti OR ‘eating’:ab,ti OR ‘diet’:ab,ti OR ‘diets’:ab,ti OR ‘cereal*’:ab,ti OR ‘bread*’:ab,ti OR ‘whole grain*’:ab,ti OR ‘juice*’:ab,ti OR ‘milk’:ab,ti OR ‘dairy’:ab,ti OR ‘meat’:ab,ti OR ‘cheese’:ab,ti OR ‘yogurt’:ab,ti OR ‘yoghurt*’:ab,ti OR ‘fruit*’:ab,ti OR ‘vegetable*’:ab,ti OR ‘egg’:ab,ti OR ‘eggs’:ab,ti OR ‘nut’:ab,ti OR ‘nuts’:ab,ti OR ‘peas’:ab,ti OR ‘beans’:ab,ti OR ‘legume*’:ab,ti OR ‘snack*’:ab,ti OR ‘candy’:ab,ti OR ‘Fast Food*’:ab,ti OR ‘seeds’:ab,ti OR ‘seafood’:ab,ti OR ‘shellfish’:ab,ti OR ‘fish’:ab,ti OR ‘soymilk’:ab,ti OR ‘wheat’:ab,ti OR ‘soy’:ab,ti OR ‘soybean’:ab,ti
#3 | Growth, body composition, and risk of obesity (pediatric) | ‘anthropometr*’:ab,ti OR ‘body fat’:ab,ti OR ‘fat mass’:ab,ti OR ‘fat free mass’:ab,ti OR ‘lean mass’:ab,ti OR ‘obese’:ab,ti OR ‘obesity’:ab,ti OR ‘underweight’:ab,ti OR ‘overweight’:ab,ti OR ‘weight status’:ab,ti OR ‘Crown-Rump Length*’:ab,ti ‘body mass index’:ab,ti OR ‘BMI’:ab,ti OR ‘adipos*’:ab,ti birth weight*:ab,ti OR ‘body weight’:ab,ti OR ‘body height’:ab,ti OR ‘body size’:ab,ti OR ‘body composition’:ab,ti OR ‘overnutrition’:ab,ti OR ‘wasting’:ab,ti OR ‘healthy weight’:ab,ti OR ‘skin fold’:ab,ti OR ‘skin folds’:ab,ti OR ‘skinfold’:ab,ti OR ‘skinfolds’:ab,ti OR ‘body weight change’/exp OR (weight NEAR/4 (decreas* OR gain* OR loss* OR chang* OR trajector*)):ab,ti OR ‘weight chart’/exp OR ‘postnatal development’/exp OR ‘physical development’/exp OR ‘overnutrition’/exp OR ‘Growth Disorder’/exp OR ‘growth’:ab,ti OR ‘overeat*’:ab,ti OR ‘over eat’:ab,ti OR ‘overfed’:ab,ti OR ‘overfeed*’:ab,ti OR ‘under-nutrition’:ab,ti OR ‘undernutrition’:ab,ti OR stunting:ab,ti OR stunted:ab,ti OR ‘weight for height’:ab,ti OR ‘stature for age’:ab,ti OR ‘weight for age’:ab,ti OR ‘height for age’:ab,ti OR ‘length for age’:ab,ti OR ‘weight for length’:ab,ti OR ‘ failure to thrive’:ab,ti
#4 | | #1 AND #2 AND #3
#5 | Limiters | #4 AND ([article]/lim OR [article in press]/lim) NOT ([animals]/lim NOT ([animals]/lim AND [humans]/lim)) AND [english]/lim NOT ([conference abstract]/lim OR [conference paper]/lim OR [conference review]/lim OR [editorial]/lim OR [erratum]/lim OR [letter]/lim OR [note]/lim OR 'retraction of publication':ab,ti OR 'retraction notice':ti OR 'retracted publication':ab,ti OR [review]/lim OR [systematic review]/lim OR [meta analysis]/lim OR 'practice guideline':ti) AND [2016–2023]/py

### Database: Cochrane Central Register of Controlled Trials (CENTRAL)

Provider: John Wiley & Sons

Date(s) Searched: October 27, 2021 (initial search); October 27, 2021 – June 1, 2023 (continuous evidence monitoring)

Dates Covered: July 20, 2016 - May 31, 2023

Table A 6 Search for Cochrane CENTRAL (Search A)

Search # | Concept | String
#1 | Infant Feeding | [mh “Infant Nutritional Physiological Phenomena”] OR (complementary OR supplementary OR wean* OR transition* OR introduction OR introducing OR introduced OR “introduction of” OR “introduction to” OR “infant feed*” OR “toddler feeding” OR IYCF OR “infant and young child feeding"):ti,ab,kw
#2 | Food and Beverage | [mh “diet”] OR [mh “meals”] OR [mh “Food and Beverages”] OR (“meal*” OR “feeding*” OR “food*” OR “beverage*” OR “eating” OR “diet” OR “diets” OR “cereal*” OR “bread*” OR “whole grain*” OR “juice*” OR “milk” OR “dairy” OR “meat” OR “cheese” OR “yogurt” OR “yoghurt*” OR “fruit*” OR “vegetable*” OR “egg” OR “eggs” OR “nut” OR “nuts” OR “peas” OR “beans” OR “legume*” OR “snack*” OR “candy” OR “Fast Food*” OR “seeds” OR “seafood” OR “shellfish” OR “fish” OR “soymilk” OR “wheat” OR “soy” OR “soybean”):ti,ab,kw
#3 | Growth, body composition, and risk of obesity (pediatric) | [mh "Adipose Tissue"] OR [mh "Body Composition"] OR [mh ^"Body Weights and Measures"] OR [mh "Body Fat Distribution"] OR [mh "Body Mass Index"] OR [mh "Body Size"] OR [mh "Skinfold Thickness"] OR [mh "Waist-Hip Ratio"] OR [mh ^Growth] OR (anthropometr* OR “body fat” OR “fat mass” OR “fat free mass” OR “lean mass” OR obese OR obesity OR underweight OR overweight OR “weight status” OR “Crown-Rump Length*” OR “body mass index” OR BMI OR adipos* OR “birth weight*” OR “body weight” OR “body height” OR “body size” OR “body composition” OR overnutrition OR wasting OR “healthy weight” OR “skin fold” OR “skin folds” OR skinfold OR skinfolds):ti,ab,kw OR [mh "Body-Weight Trajectory"] OR [mh "Weight Gain"] OR [mh ^"Weight Loss"] OR (weight NEAR/4 (decreas* OR gain* OR loss* OR chang* OR trajectory*)):ti,ab,kw OR [mh “Growth Charts”] OR [mh /GD] OR [mh ^“Growth and Development”] OR [mh Overnutrition] OR [mh “Growth Disorders”] OR (growth OR overeat* OR “over eat” OR overfed OR overfeed* OR “under-nutrition” OR undernutrition OR stunting OR stunted OR “weight for height” OR “stature for age” OR “weight for age” OR “height for age” OR “length for age” OR “weight for length” OR “failure to thrive”):ti,ab,kw
#4 | | #1 AND #2 AND #3; In Trials (Word variations have been searched); Year first published: 2016 – 2023

### Database: CINAHL

Provider: EBSCO

Date(s) Searched: October 27, 2021 (initial search); October 27, 2021 – June 1, 2023 (continuous evidence monitoring)

Dates Covered: July 20, 2016 - May 31, 2023

Table A 7 Search for CINAHL (Search A)

Search # | Concept | String
#1 | Infant Feeding | (MH “Infant Nutritional Physiology+”) OR TI (“complementary” OR “supplementary” OR “wean*” OR “transition*” OR “introduction”:ti OR “introducing” OR “introduced” OR “introduction of” OR “introduction to” OR “infant feed*” OR “toddler feeding” OR “IYCF” OR “infant and young child feeding”) OR AB (“complementary” OR “supplementary” OR “wean*” OR “transition*” OR “introduction”:ti OR “introducing” OR “introduced” OR “introduction of” OR “introduction to” OR “infant feed*” OR “toddler feeding” OR “IYCF” OR “infant and young child feeding”)
#2 | Food and Beverage | (MH “Diet+”) OR (MH “Meals+”) OR (MH “Food and Beverages+”) OR TI (“meal*” OR “feeding*” OR “food*” OR “beverage*” OR “eating” OR “diet” OR “diets” OR “cereal*” OR “bread*” OR “whole grain*” OR “juice*” OR “milk” OR “dairy” OR “meat” OR “cheese” OR “yogurt” OR “yoghurt*” OR “fruit*” OR “vegetable*” OR “egg” OR “eggs” OR “nut” OR “nuts” OR “peas” OR “beans” OR “legume*” OR “snack*” OR “candy” OR “Fast Food*” OR “seeds” OR “seafood” OR “shellfish” OR “fish” OR “soymilk” OR “wheat” OR “soy” OR “soybean”) OR AB (“meal*” OR “feeding*” OR “food*” OR “beverage*” OR “eating” OR “diet” OR “diets” OR “cereal*” OR “bread*” OR “whole grain*” OR “juice*” OR “milk” OR “dairy” OR “meat” OR “cheese” OR “yogurt” OR “yoghurt*” OR “fruit*” OR “vegetable*” OR “egg” OR “eggs” OR “nut” OR “nuts” OR “peas” OR “beans” OR “legume*” OR “snack*” OR “candy” OR “Fast Food*” OR “seeds” OR “seafood” OR “shellfish” OR “fish” OR “soymilk” OR “wheat” OR “soy” OR “soybean”)
#3 | Growth, body composition, and risk of obesity (pediatric) | (MH “Adipose Tissue+”) OR (MH “Body Composition+”) OR (MH “Body Weights and Measures”) OR (MH “Body Height”) OR (MH “Body Mass Index”) OR (MH “Body Size”) OR (MH “Body Weight+”) OR (MH “Crown-Rump Length”) OR (MH “Skinfold Thickness”) OR (MH “Obesity+”) OR (MH “Growth”) OR TI (anthropometr* OR “body fat” OR “fat mass” OR “fat free mass” OR “lean mass” OR obese OR obesity OR underweight OR overweight OR “weight status” OR “Crown-Rump Length” OR “body mass index” OR BMI OR adipos* OR “body weight” OR “body height” OR “body size” OR “body composition” OR overnutrition OR wasting OR “healthy weight” OR “skin fold” OR “skin folds” OR skinfold OR skinfolds) OR (AB anthropometr* OR “body fat” OR “fat mass” OR “fat free mass” OR “lean mass” OR obese OR obesity OR underweight OR overweight OR “weight status” OR “Crown-Rump Length” OR “body mass index” OR BMI OR adipos* OR “body weight” OR “body height” OR “body size” OR “body composition” OR overnutrition OR wasting OR “healthy weight” OR “skin fold” OR “skin folds” OR skinfold OR skinfolds) OR (MH “Weight Gain+”) OR (MH “Weight Loss”) OR TI (weight N4 (decreas* OR gain* OR maint* OR reduc* OR loss* OR chang*)) OR AB (weight N4 (decreas* OR gain* OR maint* OR reduc* OR loss* OR chang*)) OR (MH “Overnutrition”) OR (MH “Growth Disorders+”) OR TI (growth OR overeat* OR “over eat” OR overfed OR overfeed* OR “under-nutrition” OR undernutrition OR stunting OR stunted OR “weight for height” OR “stature for age” OR “weight for age” OR “height for age” OR “length for age” OR “weight for length” OR “failure to thrive”) OR AB (growth OR overeat* OR “over eat” OR overfed OR overfeed* OR “under-nutrition” OR undernutrition OR stunting OR stunted OR “weight for height” OR “stature for age” OR “weight for age” OR “height for age” OR “length for age” OR “weight for length” OR “failure to thrive”)
#4 | | S1 AND S2 AND S3
#5 | Limiters | S4 NOT ((MH “Animals+”) OR (MH “Animal Studies”)) NOT ((MH “Congresses and Conferences”) OR (MH “Literature Review”) OR (MH “Meta Analysis”) OR (MH “Systematic Review”) OR (MH “News”) OR (MH “Practice Guidelines”) OR (MH “Retracted Publication”) OR (MH “Retraction of Publication”)); Limiters - English Language, Expanders - Apply equivalent subject; Published Date July 2016 – May 31, 2023

## Search B

This search was updated to expand the definition of complementary food and beverage to include all food and drink intake between 0 and 24 months, and then run against the existing search to isolate unique results.

### Database: PubMed

Provider: U.S. National Library of Medicine

Date(s) Searched: June 1, 2023

Dates Covered: January 1, 1980 – May 31, 2023

Table A 8 Search for PubMed (Search B)

Search # | Concept | String
#1 | Infant Feeding | “Infant Nutritional Physiological Phenomena“[Mesh] OR Complementary[tiab] OR supplementary[tiab] OR wean*[tiab] OR transition*[tiab] OR introduction[ti] OR introducing[tiab] OR introduced[tiab] OR “introduction of”[tiab] OR “introduction to”[tiab] OR “infant feed*”[tiab] OR “toddler feeding”[tiab] OR IYCF[tiab] OR “infant and young child feeding”[tiab] OR ((“Infant“[MeSH] OR “Child“[MeSH] OR child*[tiab]) AND (intake*[tiab] OR consum*[tiab]))
#2 | Selected Foods | “Diet”[MeSH:NoExp] OR “Meals”[MeSH] OR “Food and Beverages“[Mesh] OR “Edible Grain“[Mesh] OR meal*[tiab] OR “plant based”[tiab] OR feeding*[tiab] OR food*[tiab] OR beverage*[tiab] OR drink[tiab] OR drinks[tiab] OR eating[tiab] OR diet[tiab] OR diets[tiab] OR cereal*[tiab] OR bread*[tiab] OR whole grain*[tiab] OR juice*[tiab] OR milk[tiab] OR dairy[tiab] OR meat[tiab] OR cheese[tiab] OR yogurt[tiab] OR yoghurt*[tiab] OR fruit*[tiab] OR vegetable*[tiab] OR egg[tiab] OR eggs[tiab] OR nut[tiab] OR nuts[tiab] OR peas[tiab] OR beans[tiab] OR legume*[tiab] OR snack*[tiab] OR candy[tiab] OR “Fast Food*”[tiab] OR seeds[tiab] OR seafood[tiab] OR shellfish[tiab] OR fish[tiab] OR soymilk[tiab] OR wheat[tiab] OR “soy”[tiab] OR “soybean”[tiab]
#3 | Growth, body composition, and risk of obesity (pediatric) | "Adipose Tissue“[Mesh] OR “Body Composition“[Mesh] OR “Body Weights and Measures“[MeSH:NoExp] OR “Body Fat Distribution“[Mesh] OR “Body Mass Index“[Mesh] OR “Body Size“[Mesh] OR “Skinfold Thickness“[Mesh] OR “Waist- Hip Ratio“[Mesh] OR “Overnutrition“[Mesh] OR “Growth“[Mesh:NoExp] OR anthropometr*[tiab] OR body fat[tiab] OR fat mass[tiab] OR fat free mass[tiab] OR lean mass[tiab] OR obese[tiab] OR obesity[tiab] OR underweight[tiab] OR overweight[tiab] OR weight status[tiab] OR head circumference[tiab] OR arm circumference[tiab] OR calf circumference[tiab] OR neck circumference[tiab] OR thigh circumference[tiab] OR waist circumference[tiab] OR waist to hip ratio[tiab] OR waist hip ratio[tiab] OR body mass index[tiab] OR BMI[tiab] OR adipos*[tiab] OR body weight[tiab] OR body height[tiab] OR body size[tiab] OR body composition[tiab] OR overnutrition[tiab] OR wasting[tiab] OR healthy weight[tiab] OR skin fold[tiab] OR skin folds[tiab] OR skinfold[tiab] OR skinfolds[tiab] OR “Body-Weight Trajectory“[Mesh] OR “Weight Gain“[MeSH] OR “Weight Loss“[MeSH:NoExp]OR weight gain*[tiab] OR weight decreas*[tiab] OR “lose weight“[tiab:~4] OR “loses weight“[tiab:~4] OR “losing weight“[tiab:~4] OR “lost weight“[tiab:~4] OR “weight loss“[tiab:~4] OR “change weight“[tiab:~4] OR “changes weight“[tiab:~4] OR “changing weight“[tiab:~4] OR “changed weight“[tiab:~4]; OR “Growth Charts”[Mesh] OR growth chart*[tiab]OR stunting[tiab] OR stunted[tiab] OR weight for height[tiab] OR stature for age[tiab] OR weight for age[tiab] OR height for age[tiab] OR length for age[tiab] OR weight for length[tiab] OR failure to thrive[tiab]
#4 | | #1 AND #2 AND #3
#5 | Updated search NOT existing search
#6 | | #5 NOT (“Animals“[Mesh] NOT (“Animals“[Mesh] AND "Humans“[Mesh])) NOT (editorial[ptyp] OR comment[ptyp] OR commentary[tiab] OR news[ptyp] OR letter[ptyp] OR review[ptyp] OR systematic review[ptyp] OR systematic review[ti] OR meta-analysis[ptyp] OR meta-analysis[ti] OR meta-analyses[ti] OR protocol[ti] OR protocols[ti] OR retracted publication[ptyp] OR retraction of publication[ptyp] OR retraction of publication[tiab] OR retraction notice[ti] OR“retracted publication”[ti] OR “Congress“[Publication Type] OR “Consensus Development Conference“[Publication Type] OR “conference abstract*”[tiab] OR “conference proceeding*”[tiab] OR “conference paper*”[tiab] OR “practice guideline“[ptyp] OR “practice guideline“[ti]); Language: English; Publication Date: 1980/01/01–3000/12/12

### Database: Embase

Provider: Elsevier

Date(s) Searched: Date(s) Searched: June 1, 2023

Dates Covered: January 1, 1980 – May 31, 2023

Table A 9 Search for Embase (Search B)

Search # | Concept | String
#1 | Infant Feeding | ‘Infant Nutrition’/exp OR ‘complementary’:ab,ti OR ‘supplementary’:ab,ti OR ‘wean*’:ab,ti OR ‘transition*’:ab,ti OR ‘introduction’:ti OR ‘introducing’:ab,ti OR ‘introduced’:ab,ti OR ‘introduction of’:ab,ti OR ‘introduction to’:ab,ti OR ‘infant feed*’:ab,ti OR ‘toddler feeding’:ab,ti OR ‘IYCF’:ab,ti OR ‘infant and young child feeding’:ab,ti OR ((‘Child’/exp OR child*:ab,ti) AND (‘intake*’:ab,ti OR ‘consum*’:ab,ti))
#2 | Selected Foods | ‘diet’/de OR ‘meal’/exp OR ‘Food’/exp OR ‘Beverages’/exp OR ‘meal*’:ab,ti OR ‘plant based’:ab,ti OR ‘feeding*’:ab,ti OR ‘food*’:ab,ti OR ‘beverage*’:ab,ti OR ‘drink’:ab,ti OR ‘drinks’:ab,ti OR ‘eating’:ab,ti OR ‘diet’:ab,ti OR ‘diets’:ab,ti OR ‘cereal*’:ab,ti OR ‘bread*’:ab,ti OR ‘whole grain*’:ab,ti OR ‘juice*’:ab,ti OR ‘milk’:ab,ti OR ‘dairy’:ab,ti OR ‘meat’:ab,ti OR ‘cheese’:ab,ti OR ‘yogurt’:ab,ti OR ‘yoghurt*’:ab,ti OR ‘fruit*’:ab,ti OR ‘vegetable*’:ab,ti OR ‘egg’:ab,ti OR ‘eggs’:ab,ti OR ‘nut’:ab,ti OR ‘nuts’:ab,ti OR ‘peas’:ab,ti OR ‘beans’:ab,ti OR ‘legume*’:ab,ti OR ‘snack*’:ab,ti OR ‘candy’:ab,ti OR ‘Fast Food*’:ab,ti OR ‘seeds’:ab,ti OR ‘seafood’:ab,ti OR ‘shellfish’:ab,ti OR ‘fish’:ab,ti OR ‘soymilk’:ab,ti OR ‘wheat’:ab,ti OR ‘soy’:ab,ti OR ‘soybean’:ab,ti
#3 | Growth, body composition, and risk of obesity (pediatric) | ‘adipose tissue’/exp OR ‘body composition’/exp OR ‘anthropometry’/de OR ‘body mass’/exp OR ‘anthropometric parameters’/exp OR ‘skinfold thickness’/exp OR ‘overnutrition’/exp OR ‘growth’/de OR ‘anthropometr*’:ab,ti OR ‘body fat’:ab,ti OR ‘fat mass’:ab,ti OR ‘fat free mass’:ab,ti OR ‘lean mass’:ab,ti OR ‘obese’:ab,ti OR ‘obesity’:ab,ti OR ‘underweight’:ab,ti OR ‘overweight’:ab,ti OR ‘weight status’:ab,ti OR ‘head circumference’:ab,ti OR ‘arm circumference’:ab,ti OR ‘calf circumference’:ab,ti OR ‘neck circumference’:ab,ti OR ‘thigh circumference’:ab,ti OR ‘waist circumference’:ab,ti OR ‘waist to hip ratio’:ab,ti OR ‘waist hip ratio’:ab,ti OR ‘body mass index’:ab,ti OR ‘BMI’:ab,ti OR ‘adipos*’:ab,ti OR ‘body weight’:ab,ti OR ‘body height’:ab,ti OR ‘body size’:ab,ti OR ‘body composition’:ab,ti OR ‘overnutrition’:ab,ti OR ‘wasting’:ab,ti OR ‘healthy weight’:ab,ti OR ‘skin fold*’:ab,ti OR ‘skinfold*’:ab,ti OR ‘body weight management’/exp OR ‘body weight change’/exp OR (weight NEAR/4 (decreas* OR gain* OR loss* OR chang*)):ab,ti OR ‘weight chart’/exp OR ‘growth chart*’:ab,ti OR stunting:ab,ti OR stunted:ab,ti OR ‘weight for height’:ab,ti OR ‘stature for age’:ab,ti OR ‘weight for age’:ab,ti OR ‘height for age’:ab,ti OR ‘length for age’:ab,ti OR ‘weight for length’:ab,ti OR ‘ failure to thrive’:ab,ti
#4 | | #1 AND #2 AND #3
#5 | Updated search NOT existing search
#6 | | #5 AND ([article]/lim OR [article in press]/lim) NOT ([animals]/lim NOT ([animals]/lim AND [humans]/lim)) AND [english]/lim NOT ([conference abstract]/lim OR [conference paper]/lim OR [conference review]/lim OR [editorial]/lim OR [erratum]/lim OR [letter]/lim OR [note]/lim OR 'retraction of publication':ab,ti OR 'retraction notice':ti OR 'retracted publication':ab,ti OR [review]/lim OR [systematic review]/lim OR [meta analysis]/lim OR 'practice guideline':ti) AND [1980–2023]/py

### Database: Cochrane Central Register of Controlled Trials (CENTRAL)

Provider: John Wiley & Sons

Date(s) Searched: June 1, 2023

Dates Covered: January 1, 1980 – May 31, 2023

Table A 10 Search for Cochrane CENTRAL (Search B)

Search # | Concept | String
#1 | Infant Feeding | [mh “Infant Nutritional Physiological Phenomena”] OR (complementary OR supplementary OR wean* OR transition* OR introduction OR introducing OR introduced OR “introduction of” OR “introduction to” OR “infant feed*” OR “toddler feeding” OR IYCF OR “infant and young child feeding"):ti,ab,kw OR (([mh "Infant"] OR [mh "Child"] OR child*:ti,ab,kw) AND (intake* OR consum*)):ti,ab,kw
#2 | Selected Foods | [mh ^“diet”] OR [mh “meals”] OR [mh “Food and Beverages”] OR (meal* OR “plant based” OR feeding* OR “food*” OR beverage* OR drink OR drinks OR “eating” OR “diet” OR “diets” OR cereal* OR bread* OR “whole grain” OR “whole grains” OR juice* OR “milk” OR “dairy” OR “meat” OR “cheese” OR yogurt* OR yoghurt* OR fruit* OR vegetable* OR “egg” OR “eggs” OR “nut” OR “nuts” OR “peas” OR “beans” OR legume* OR “snack*” OR “candy” OR “Fast Food” OR “fast foods” OR “seeds” OR “seafood” OR “shellfish” OR “fish” OR “soymilk” OR “wheat” OR “soy” OR “soybean”):ti,ab,kw
#3 | Growth, body composition, and risk of obesity (pediatric) | [mh "Adipose Tissue"] OR [mh "Body Composition"] OR [mh ^"Body Weights and Measures"] OR [mh "Body Fat Distribution"] OR [mh "Body Mass Index"] OR [mh "Body Size"] OR [mh "Skinfold Thickness"] OR [mh "Waist-Hip Ratio"] OR [mh Overnutrition] OR [mh ^Growth] OR (anthropometr* OR “body fat” OR “fat mass” OR “fat free mass” OR “lean mass” OR obese OR obesity OR underweight OR overweight OR “weight status” OR “head circumference” OR “arm circumference” OR “calf circumference” OR “neck circumference” OR “thigh circumference” OR “waist circumference” OR “waist to hip ratio” OR “waist hip ratio” OR “body mass index” OR BMI OR adipos* OR “body weight” OR “body height” OR “body size” OR “body composition” OR overnutrition OR wasting OR “healthy weight” OR “skin fold” OR “skin folds” OR skinfold OR skinfolds):ti,ab,kw OR [mh "Body-Weight Trajectory"] OR [mh "Weight Gain"] OR [mh ^“Weight Loss”] OR ((weight NEAR/4 (decreas* OR gain* OR loss* OR chang*)) OR [mh “Growth Charts”] OR “growth chart*” OR stunting OR stunted OR “weight for height” OR “stature for age” OR “weight for age” OR “height for age” OR “length for age” OR “weight for length” OR “ failure to thrive”):ti,ab,kw
#4 | | #1 AND #2 AND #3
#5 | Updated search NOT existing search
#6 | | #5 In Trials (Word variations have been searched); Date Range: 1980–2023; Language: English

### Database: CINAHL

Provider: EBSCO

Date(s) Searched: June 1, 2023

Dates Covered: January 1, 1980 – May 31, 2023

Table A 11 Search for CINAHL (Search B)

Search # | Concept | String
#1 | Infant Feeding | (MH "Infant Nutritional Physiology+") OR TI (“complementary” OR “supplementary” OR “wean*” OR “transition*” OR “introduction”:ti OR “introducing” OR “introduced” OR “introduction of” OR “introduction to” OR “infant feed*” OR “toddler feeding” OR “IYCF” OR “infant and young child feeding”) OR AB (“complementary” OR “supplementary” OR “wean*” OR “transition*” OR “introduction”:ti OR “introducing” OR “introduced” OR “introduction of” OR “introduction to” OR “infant feed*” OR “toddler feeding” OR “IYCF” OR “infant and young child feeding”) OR TI (((MH “Child") OR child*)) AND (intake*[tiab] OR consum*)) OR AB (((MH “Child") OR child*)) AND (intake*[tiab] OR consum*))
#2 | Selected Foods | (MH "Diet") OR (MH "Meals+") OR (MH "Food and Beverages+") OR TI (“meal*” OR “plant based” OR “feeding*” OR “food*” OR “beverage*” OR “drink” OR “drinks” OR “eating” OR “diet” OR “diets” OR “cereal*” OR “bread*” OR “whole grain*” OR “juice*” OR “milk” OR “dairy” OR “meat” OR “cheese” OR “yogurt” OR “yoghurt*” OR “fruit*” OR “vegetable*” OR “egg” OR “eggs” OR “nut” OR “nuts” OR “peas” OR “beans” OR “legume*” OR “snack*” OR “candy” OR “Fast Food*” OR “seeds” OR “seafood” OR “shellfish” OR “fish” OR “soymilk” OR “wheat” OR “soy” OR “soybean”) OR AB (“meal*” OR “plant based” OR “feeding*” OR “food*” OR “beverage*” OR “drink” OR “drinks” OR “eating” OR “diet” OR “diets” OR “cereal*” OR “bread*” OR “whole grain*” OR “juice*” OR “milk” OR “dairy” OR “meat” OR “cheese” OR “yogurt” OR “yoghurt*” OR “fruit*” OR “vegetable*” OR “egg” OR “eggs” OR “nut” OR “nuts” OR “peas” OR “beans” OR “legume*” OR “snack*” OR “candy” OR “Fast Food*” OR “seeds” OR “seafood” OR “shellfish” OR “fish” OR “soymilk” OR “wheat” OR “soy” OR “soybean”)
#3 | Growth, body composition, and risk of obesity (pediatric) | (MH “Adipose Tissue+”) OR (MH "Body Composition+") OR (MH "Body Weights and Measures") OR (MH "Arm Circumference") OR (MH "Body Height") OR (MH "Body Mass Index") OR (MH "Body Size") OR (MH "Body Weight+") OR (MH "Crown-Rump Length") OR (MH "Waist Circumference") OR (MH "Waist-Hip Ratio") OR (MH "Skinfold Thickness") OR (MH "Obesity+") OR (MH "Overnutrition") OR (MH "Growth") OR (TI anthropometr* OR “body fat” OR “fat mass” OR “fat free mass” OR “lean mass” OR obese OR obesity OR underweight OR overweight OR “weight status” OR “head circumference” OR “arm circumference” OR “calf circumference” OR “neck circumference” OR “thigh circumference” OR “waist circumference” OR “waist to hip ratio” OR “waist hip ratio” OR “body mass index” OR BMI OR adipos* OR “body weight” OR “body height” OR “body size” OR “body composition” OR overnutrition OR wasting OR “healthy weight” OR “skin fold” OR “skin folds” OR skinfold OR skinfolds) OR (AB anthropometr* OR “body fat” OR “fat mass” OR “fat free mass” OR “lean mass” OR obese OR obesity OR underweight OR overweight OR “weight status” OR “head circumference” OR “arm circumference” OR “calf circumference” OR “neck circumference” OR “thigh circumference” OR “waist circumference” OR “waist to hip ratio” OR “waist hip ratio” OR “body mass index” OR BMI OR adipos* OR “body weight” OR “body height” OR “body size” OR “body composition” OR overnutrition OR wasting OR “healthy weight” OR “skin fold” OR “skin folds” OR skinfold OR skinfolds) OR (MH "Body Weight Changes") OR (MH "Weight Gain+") OR (MH "Weight Loss") OR (TI (weight N4 (decreas* OR gain* OR loss* OR chang*))) OR (AB (weight N4 (decreas* OR gain* OR loss* OR chang*))) OR (TI “growth chart*” OR stunting OR stunted OR “weight for height” OR “stature for age” OR “weight for age” OR “height for age” OR “length for age” OR “weight for length” OR “failure to thrive”) OR (AB “growth chart*” OR stunting OR stunted OR “weight for height” OR “stature for age” OR “weight for age” OR “height for age” OR “length for age” OR “weight for length” OR “failure to thrive”)
#4 | | S1 AND S2 AND S3
#5 | Updated search NOT existing search
#6 | | S5 NOT ((MH “Animals+”) OR (MH “Animal Studies”)) NOT ((MH “Congresses and Conferences”) OR (MH “Literature Review”) OR (MH “Meta Analysis”) OR (MH “Systematic Review”) OR (MH “News”) OR (MH “Practice Guidelines”) OR (MH “Retracted Publication”) OR (MH “Retraction of Publication”)); Limiters – English Language, Expanders – Apply equivalent subject; Publication Year: 1980–2023