# Appendix 2 Conclusion statements from the existing systematic reviews

Table A 2 Conclusion statements from the existing systematic reviews for the research question: What is the relationship between complementary feeding and growth, body composition, and risk of obesity?

Citation | Conclusion statements and grades
English LK, Obbagy JE, Wong YP, Psota TL, Nadaud P, Johns K, Terry N, Butte NF, Dewey KG, Fleischer DM, Fox MK, Greer FR, Krebs NF, Scanlon KS, Casavale KO, Spahn JM, Stoody E. Timing of Introduction of Complementary Foods and Beverages and Growth, Size, and Body Composition: A Systematic Review. April 2019. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: 10.52570/NESR.PB242018.SR0305 | - Moderate evidence suggests that first introduction of any complementary food or beverage (CFB) between 4–5 months compared to approximately 6 months of age is not associated with weight status, body composition, body circumferences, weight, or length among generally healthy, full-term infants. (Grade: Moderate); - Limited evidence suggests that introducing CFB before 4 months of age may be associated with higher odds of overweight/obesity. (Grade: Limited); - There is not enough evidence to determine the relationship between introduction of CFB at 7 months of age or older on growth, size, or body composition. (Grade: Grade Not Assignable)
English LK, Obbagy JE, Wong YP, Psota TL, Nadaud P, Johns K, Terry N, Butte NF, Dewey KG, Fleischer DM, Fox MK, Greer FR, Krebs NF, Scanlon KS, Casavale KO, Spahn JM, Stoody E. Types and Amounts of Complementary Foods and Beverages and Growth, Size, and Body Composition: A Systematic Review. April 2019. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: 10.52570/NESR.PB242018.SR0306 | - Moderate evidence indicates that higher versus lower meat intake or meat versus iron-fortified cereal intake over a short duration (~3mo) during the complementary feeding period does not favorably or unfavorably influence growth, size, and/or body composition. There is insufficient evidence to determine a relationship between meat intake and prevalence/incidence of overweight or obesity. (Grade: Moderate); - Limited evidence suggests that type or amount of cereal given does not favorably or unfavorably influence growth, size, body composition, and/or prevalence/incidence of overweight or obesity. (Grade: Limited); - Moderate evidence suggests that consumption of complementary foods with different fats and/or fatty acid composition does not favorably or unfavorably influence growth, size, or body composition. There is not enough evidence to determine a relationship between consumption of complementary foods with different fats and/or fatty acid composition and/or prevalence/incidence of overweight or obesity. (Grade: Moderate); - Limited evidence suggests that sugar sweetened beverage consumption during the complementary feeding period is associated with increased risk of obesity in childhood, but is not associated with other measures of growth, size, and body composition. (Grade: Limited); - Limited evidence showed a positive association between juice intake and infant weight-for-length and child BMI z-scores. (Grade: Limited); - No conclusion could be made about the relationship between other complementary foods (vegetables, fruit, dairy products and/or cow’s milk, cereal-based products, milk-cereal drink, and/or categories such as “ready-made foods“) and growth, size, body composition, and/or prevalence/incidence of overweight or obesity. (Grade: Grade Not Assignable)