# Appendix 1 Abbreviations

Table A 1 List of abbreviations
Abbreviation: Full name
BMI: Body mass index
BMIZ: Body mass index z-score
CAPS: Childhood Asthma Prevention Study
CDC: Centers for Disease Control and Prevention
FFQ: Food frequency questionnaire
FPL: Federal poverty level
GEHM: Global Exploration of Human Milk
HAZ: Height-for-age z-score
HHS: United States Department of Health and Human Services
IFPS II: Infant Feeding Practices Study II
LAZ: Length-for-age z-score
LoTiS: Longitudinal Twin Study
NESR: Nutrition Evidence Systematic Review
NICHD: Eunice Kennedy Shriver National Institutes of Child Human Development
NRCT: Nonrandomized controlled trial
PCS: Prospective cohort study
RCT: Randomized controlled trial
SDS: Standard deviation score
SEP: Socioeconomic position
SSB: Sugar sweetened beverage
USDA: United States Department of Agriculture
WAZ: Weight-for-age z-score
WHO: World Health Organization
WHZ: Weight-for-height z-score
WIC: Special Supplemental Nutrition Program for Women, Infants, and Children
WIC ITFPS-2: WIC Infant and Toddler Feeding Practices Study-2
WLZ: Weight-for-length z-score