# References of the articles included in the systematic review

1 Ho J, Pedersen SD, Virtanen H, Nettel-Aguirre A, Huang C. Family intervention for obese/overweight children using portion control strategy (FOCUS) for weight control: a randomised controlled trial. Journal article. Global pediatric health. 2016;3:1–7. doi: 10.1177/2333794X16669014
2 Cook CM, McCormick CN, Knowles M, Kaden VN. A Commercially Available Portion-Controlled Diet Program Is More Effective for Weight Loss than a Self-Directed Diet: Results from a Randomized Clinical Trial. Front Nutr. 2017;4:55. doi:10.3389/fnut.2017.00055 29164129
3 Faucher MA, Mobley J. A community intervention on portion control aimed at weight loss in low-income Mexican American women. J Midwifery Womens Health. Jan-Feb 2010;55(1):60–4. doi:10.1016/j.jmwh.2009.03.014 20129231
4 French SA, Mitchell NR, Wolfson J, Portion size effects on weight gain in a free living setting. Obesity (Silver Spring). Jun 2014;22(6):1400–5. doi:10.1002/oby.20720 24510841
5 Melanson KJ, Summers A, Nguyen V, Body composition, dietary composition, and components of metabolic syndrome in overweight and obese adults after a 12-week trial on dietary treatments focused on portion control, energy density, or glycemic index. Nutr J. Aug 27 2012; 11:57. doi: 10.1186/1475-2891-11-57 22925169
6 Poelman MP, de Vet E, Velema E, de Boer MR, Seidell JC, Steenhuis IH. PortionControl@HOME: results of a randomized controlled trial evaluating the effect of a multi-component portion size intervention on portion control behavior and body mass index. Ann Behav Med. Feb 2015;49(1):18–28. doi: 10.1007/s12160-014-9637-4 25142041
7 Eykelenboom M, van Stralen MM, Poelman MP, Steenhuis IHM. Patterns of weight loss and their determinants in a sample of adults with overweight and obesity intending to lose weight. Nutrition & Dietetics. Apr 2020;77(2):240–246. doi:10.1111/1747-0080.12489 30402896
8 Rock CL, Flatt SW, Pakiz B, Barkai HS, Heath DD, Krumhar KC. Randomized clinical trial of portion-controlled prepackaged foods to promote weight loss. Obesity (Silver Spring). Jun 2016;24(6): 1230–7. doi:10.1002/oby.21481 27225596
9 Rolls BJ, Roe LS, James BL, Sanchez CE. Does the incorporation of portion-control strategies in a behavioral program improve weight loss in a 1-year randomized controlled trial? Int J Obes (Lond). Mar 2017;41(3):434–442. doi: 10.1038/ijo.2016.217 27899807
10 Roe LS, Rolls BJ. Which strategies to manage problem foods were related to weight loss in a randomized clinical trial? Appetite. Aug 1 2020;151:104687. doi:10.1016/j.appet.2020.104687 32234531
11 Tapsell LC, Batterham MJ, Thorne RL, O'Shea JE, Grafenauer SJ, Probst YC. Weight loss effects from vegetable intake: a 12-month randomised controlled trial. Eur J Clin Nutr. Jul 2014;68(7):778–85. doi: 10.1038/ejcn.2014.39 24667750
12 Webber KH, Rose SA. A pilot Internet-based behavioral weight loss intervention with or without commercially available portion-controlled foods. Obesity (Silver Spring). Sep 2013;21(9):E354–9. doi: 10.1002/oby.20331 23408562
13 Blumfield ML, Schreurs M, Rollo ME, MacDonald-Wicks LK, Kokavec A, Collins CE. The association between portion size, nutrient intake and gestational weight gain: a secondary analysis in the WATCH study 2006/7. J Hum Nutr Diet. Jun 2016;29(3):271–80.26249316