# Summary of conclusion statements and grades

The 2025 Dietary Guidelines Advisory Committee answered the systematic review question, “What is the relationship between portion size and growth, body composition, and risk of obesity?”, with the following conclusion statements.^*^ The grades reflect the strength of the evidence underlying the conclusion statements.

* A conclusion statement is carefully constructed, based on the evidence reviewed, to answer the systematic review question. A conclusion statement does not draw implications and should not be interpreted as dietary guidance.

### Young children, children, and adolescents

A conclusion statement cannot be drawn about the relationship between portion sizes consumed by young children, children, and adolescents and growth, body composition, and risk of obesity because there is not enough evidence available. (Grade: Grade Not Assignable)

### Adults and older adults

A conclusion statement cannot be drawn about the relationship between portion sizes consumed by adults and older adults and body composition or risk of obesity because of inconsistency in the interventions, comparators, and outcomes in the body of evidence. (Grade: Grade Not Assignable)

### Pregnancy

A conclusion statement cannot be drawn about the relationship between portion sizes consumed during pregnancy and gestational weight gain because there is not enough evidence available. (Grade: Grade Not Assignable)

### Postpartum

A conclusion statement cannot be drawn about the relationship between portion sizes consumed during postpartum and postpartum weight change because there is no evidence available. (Grade: Grade Not Assignable)

## Research recommendations

- To complement studies focused on weight loss, design and conduct portion size interventions of longer duration on examining weight gain prevention, healthy growth patterns, dietary and eating behaviors, and diet quality.
- Measure baseline total energy intake and change in total energy intake with the portion size intervention.
- Apply best practices for nutrition research by measuring and reporting adherence data and conducting adequately powered trials.
- Ensure adequate representation of populations in which evidence is lacking including young children, adolescents, individuals during pregnancy and postpartum, older adults, and among diverse populations (e.g. minoritized racial and/or ethnic groups, individuals of various socioeconomic positions, individuals of various geographical locations, individuals with various countries of birth and/or length of time in the U.S.)
- Include a variety of pre-portioned meal options such as commercially prepared products and researcher prepared meals.
- Conduct research to determine the effects of portion control in the context of medically tailored meals (food is medicine).
- Conduct both longitudinal and randomized trials during pregnancy and postpartum ensuring that this population is following clinical recommendations for appropriate weight management.
- Focus on prevention of excessive weight gain in young children, children, and adolescents.
- Conduct family-based studies that examine the intervention/exposures at the family level and assesses outcomes among all family members.

Table 8 Evidence examining the relationship between portion size and growth, body composition, and risk of obesity in young children, children, and adolescents^a^

Study and Population Characteristics | Intervention, Comparator, and Outcomes | Results | Confounding and Study Limitations
Ho, 2016^1^; RCT-Parallel, Family Intervention for Obese/Overweight Children Using Portion Control Strategy (FOCUS), Canada Baseline N=99, Analytic N=73 (Attrition: 26%); Study objective: To assess the effect of a family intervention using a portion control tool on BMI z-score in children; Participant characteristics at baseline:; Children and adolescents, 8–16 y, BMI >85th percentile for age and gender; - [underlined: Age]: Mean (SD): 11 (2.2) y; - [underlined: Female]: 57%; - [underlined: Race and/or ethnicity]: NR; - [underlined: Socioeconomic position]: NR; - [underlined: Anthropometry]:; BMI: Mean (SD) 29.1 (5.6) kg/m^2^;; BMI z-score: 2.7 (0.4); - [underlined: Physical activity]: NR; - [underlined: Smoking]: NR; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Those currently taking a weight loss medication, enrolled in any organized weight loss programs or exercise programs, consumed more than 30% of all meals at restaurants, history of GI disorder, psychiatric illness under the care of a physician, Cushing's syndrome, hypothalamic or genetic etiology of obesity, uncontrolled or untreated thyroid disease, a current diagnosis of cancer, history of eating disorder, surgery in past 3 months or planned in next 6 months, other chronic illness affecting weight | Intervention:; [underlined: Portion Control Group]: Counseling + calibrated portion control plate and breakfast bowl; [underlined: Control Group]: Counseling; Duration: 6 months; Compliance: 25 were lost to follow up (10 intervention, 15 control) at 3 months; 1 was lost to follow up in intervention group at 6 months; Outcomes and assessment methods:; Baseline, 3 and 6 months; Weight, height, and waist circumference were measured by study personnel. | Weight change, kg (baseline, 6 mo); Portion control tool: 2.55 (5.16); Control: 2.67 (5.00) p=0.92; Change in waist circumference, cm (baseline, 6 mo); Portion control tool: −3.09 (19.2); Control: 1.94 (18.4) p=0.26; Change in BMI, kg/m^2^ (baseline, 6 mo); Portion control tool: 0.02 (1.64); Control: 0.14 (1.52) p=0.74; Change in BMI z score; Portion control tool: −0.15 (0.30); Control: −0.10 (0.22) p=0.42 | Model adjustments:; - TEI: No; - Other: ITT and per-protocol analyses; Limitations:; - Concerns with potential for deviations from intended intervention (study was stopped before targeted enrollment when new pediatric weight management clinic opened); Differences in attrition (high loss to follow up) that were not accounted for; Not sufficiently powered; Funding:; Alberta Children's Hospital Foundation. Tools donated by The Diet Plate

a Abbreviations: RCT: Randomized Controlled Trial; y: years; BMI: Body Mass Index; SD: Standard Deviations; NR: Not Reported; TEI: Total Energy Intake; Kg: kilogram; Mo: month; kg/m^2^: kilogram per meters squared; ITT: Intent to treat

Table 9 Risk of bias for randomized controlled trials examining portion size and growth, body composition, and risk of obesity in young children, children, and adolescents^a^

Article | Randomization | Deviations from intended interventions (effect of assignment) or (per-protocol) | Missing outcome data | Outcome measurement | Selection of the reported result | Overall risk of bias
Ho, 2016 ^1^ | LOW | HIGH | HIGH | LOW | LOW | HIGH

a Possible ratings of low, some concerns, or high determined using the "Cochrane Risk-of-bias 2.0" (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2019 version)” ( Sterne JAC, Savović J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ 2019; 366: 14898. )

Table 10 Evidence examining the relationship between portion size and body composition or risk of obesity in adults and older adults^a^

Study and Population Characteristics | Intervention, Comparator, and Outcomes | Results | Confounding and Study Limitations
Cook, 2017^2^; RCT-Parallel, U.S.; Baseline N=78, Analytic N=76 (Attrition: 3%); Study objective: To examine changes in weight and related outcomes in response to a commercial weight loss program compared to a self-directed diet in adults with overweight or obesity; Participant characteristics at baseline: Adults, 18–70 y, BMI 25–44.99 kg/m^2^; - [underlined: Age]: Mean (SD): 50.4 (11) y; - [underlined: Female]: 78%; - [underlined: Race and/or ethnicity]: White: 71%; Black/African American: ~20%; Multiracial: 4%; Other: 5%; - [underlined: Socioeconomic position]: NR; - [underlined: Anthropometry]: BMI: 34.4 kg/m^2^; - [underlined: Physical activity]: NR; - [underlined: Smoking]: NR; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Pregnant or lactating, premenopausal women not willing to take contraception during study, weight change of ≥4.5 kg or used prescription medications for weight-reducing purposes within 6 months of screening, or who used weight loss supplements or other commercially available products/programs with the intent to lose weight, clinically significant abnormal routine laboratory test results, medical history indicating clinically relevant cardiac, renal, hepatic, endocrine (including diabetes mellitus at screening), pulmonary, biliary, gastrointestinal, pancreatic, or neurologic disorders; cancer in the past 2 years; known sensitivity to any of the ingredients in the study foods; a history of weight-reducing surgery; a history of eating disorders, extreme dietary habits, or alcohol abuse; use of thyroid hormones (except stable dose replacement therapy for at least 2 months prior to screening); or systemic corticosteroid use within 4 weeks of screening | Intervention:; [underlined: Commercial program]: Instructed to consume pre-packaged portion-controlled foods for ~60% daily energy intake, provided macronutrient-related advice; [underlined: Self-selected diet]: Provided with DASH diet counseling; Duration: 16 weeks; Compliance: NR; Outcomes and assessment methods: Weight and body circumferences: 1, 2, 3, 4, 8, 12, and 16 weeks; Fat mass: 0, 4, 8, 16 weeks; Weight and body circumference (chest, waist, hip, upper arm, and thigh) were measured by study personnel; Fat mass and fat-free mass were measured using DEXA | Baseline, week 16 change Total fat mass (kg); [underlined: Commercial diet]: 39.7 (9.1), −4.4 (−5.7, −3.1); [underlined: Self-selected diet]:; 44.4 (10.7), −1.2 (−2.1, −0.4); P, group <0.05; Body fat (%); [underlined: Commercial diet]:; 44.0 (6.2), −2.3 (−3.2, −1.4); [underlined: Self-selected diet]:; 45.9 (6.9), −0.4 (−1.0, 0.2); P, group <0.05; Android fat mass (kg); [underlined: Commercial diet]:; 3.83 (1.18), −0.66 (−0.91, −0.40); [underlined: Self-selected diet]:; 4.21 (1.17), −0.24 (−0.47, −0.01); P, group <0.05; Abdominal visceral fat mass (kg); [underlined: Commercial diet]:; 1.43 (0.77), −0.21 (−0.40, −0.02); [underlined: Self-selected diet]:; 1.53 (0.64), −0.01 (−0.14, 0.13); P, group <0.05; Weight (kg) (mean, 95% CI):; [underlined: Commercial diet]:; 92.1 (16.0), −5.9 (−7.5, −4.3); [underlined: Self-selected diet]:; 98.9 (18.6), −1.8 (−2.9, −0.8); P, group <0.05 | Model adjustments:; - Other: Intervention; Limitations:; - Did not describe adherence; Groups received different dietary advice, in addition to pre-packaged foods vs. self-selection; analysis plan registered post hoc; Funding:; Nutrisystem, Inc
Faucher, 2010^3^; RCT-Parallel, U.S.; Baseline N=24, Analytic N=19 (Attrition: 21%); Study objective: To determine if a nutritional intervention aimed at portion control leads to significant weight loss in a community of low-income Mexican American women; Participant characteristics at baseline: Adult women with overweight or obesity who wanted to lose weight; - [underlined: Age]: Mean (SD): 34.89 (4.8) y; - [underlined: Female]: 100%; - [underlined: Race and/or ethnicity]:; Mexican country of origin: 95%; Honduras country of origin: 5%; - [underlined: Socioeconomic position]: Work outside home: 21%; Married: 68%; - [underlined: Anthropometry]: BMI: 33.9 (6.0) kg/m^2^; - [underlined: Physical activity]: NR; - [underlined: Smoking]: NR; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Those who did not want to lose weight; BMI <25; currently diagnosed with depression or anxiety disorder; to become pregnant or pregnant; taking steroids (including oral contraceptive); psychotropic, antidepressant, or beta-blocker meds; contraindications to exercise; males | Intervention:; [underlined: Portion Control Intervention]: 4 group classes on portion control; [underlined: Standard care]: 1 counseling visit on portion control, exercise, other diet advice; Duration: 20 weeks; Compliance: 1 withdrew from standard group before visit; 2 did not return for standard care appointment; 2 withdrew from intervention group before first class for work conflict; Outcomes and assessment methods:; Baseline, 20 weeks (not clearly stated); Baseline weight measured by study personnel, Final measurements NR | Baseline, 20 weeks; Weight change, lb. Mean (SD); Control Group; [underlined: Baseline]: 193.3 (49.7); [underlined: Weight change]: −2.8 (10.2) NS; Intervention Group; [underlined: Baseline]: 183.3 (36.0); [underlined: Weight change]: −6.5 (7.5) p=0.47 | Model adjustments:; - Other: Additional analyses included exercise and self-weighing though those measures were not discussed in methods; Limitations:; - Methods for randomization and concealment NR; Not sufficiently powered; Did not account for loss to follow-up; Outcome measurement not specified; No preregistered data analysis plan; Funding:; Baylor University and The Louise Herrington School of Nursing
French, 2014^4^; RCT-Parallel, U.S.; Baseline N=233, Analytic N=229 (Attrition: 2%); Study objective: To examine the effect of weekday exposure over 6 months to different lunch sizes on energy intake and body weight in a free-living sample of working adults; Participant characteristics at baseline: Adults 18–60y; - [underlined: Age]: Mean (SD): 42.6 (11.2) y; - [underlined: Female]: 67%; - [underlined: Race and/or ethnicity]: White: 69%; - [underlined: Socioeconomic position]: College degree or more: 52%; Income, $40–80,000: 42%; >$80,000: 37%; Married/living with partner: 59%; - [underlined: Anthropometry]: BMI: 29.8 (6.4) kg/m^2^; - [underlined: Physical activity]: Moderate/vigorous, mins/d: 27.5 (17.2); - [underlined: Smoking]: 100% nonsmokers; - [underlined: TEI]: Baseline: 2,012 (679) kcal/d; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Smokers, non-English speaking, taking medications that affect appetite or body weight; unable to pick up lunches; allergic to or unwilling to eat study foods; currently on a diet to lose weight; eating disorder; planning to move; currently taking part in another research study; currently pregnant, nursing, or pregnant in the last 12 months | Intervention:; [underlined: Box lunch]: 400kcal, Mon-Fri; [underlined: Box lunch]: 800kcal, Mon-Fri; [underlined: Box lunch]: 1600kcal, Mon-Fri; [underlined: Contro]l: Habitual lunch intake; Duration: 6 months; Compliance: 91% of the lunches were picked up; Outcomes and assessment methods:; Baseline, 1 month, 3 month, 6 month; Weight was measured by study personnel using standardized protocols. | Weight change, kg, from baseline to 6 mo:; [underlined: 400kcal box lunch]: −0.1 (0.43); [underlined: 800kcal box lunch]: −0.1 (0.42); [underlined: 1600kcal box lunch]: 1.1 (0.44); [underlined: Control]: 1.1 (0.42); P=NS between groups; Rate of weight change, kg/month, from baseline to 6 mo:; [underlined: 400kcal box lunch]: −0.01; [underlined: 800kcal box lunch]: −0.01; [underlined: 1600kcal box lunch]: 0.19; [underlined: Contro]l: 0.24; P<0.05 for 1600kcal, control vs. 400kcal and 800kcal | Model adjustments:; - TEI: Yes; - Other: Job type, education; Limitations:; - Methods for randomization concealment NR, and concerns that randomization was not successful due to baseline differences; Minimal information provided about adherence to the study protocol; Unclear why rate of change outcomes was reported but mean data at the same timepoints were not; No preregistered data analysis plan; Funding:; NIH
Melanson, 2012^5^; RCT-Parallel, U.S.; Baseline N=157, Analytic N=135 (Attrition: 14%); Study objective: To compare effects of three dietary approaches to weight loss on body composition, dietary composition and risk factors for metabolic syndrome (MetS); Participant characteristics at baseline: Adults, sedentary, weight stable, aged 25–50 y with a BMI of 27–35 kg/m^2^; - [underlined: Age]: Mean (SD): 39 (7) y; - [underlined: Female]: 88%; - [underlined: Race and/or ethnicity]: NR; - [underlined: Socioeconomic position]: NR; - [underlined: Anthropometry]:; BMI: 31.4 (2.4) kg/m^2^;; Waist circumference: 91.3 (8.7) cm;; Body fat %: 46.1% (5.4) %; - [underlined: Physical activity]: NR; - [underlined: Smoking]: NR; - [underlined: TEI]: 2,014.3 (620) kcal; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Those taking medications or over the counter supplements for weight loss, diagnosis with diabetes mellitus, uncontrolled hypertension, orthopedic limitations, eating disorders, pregnancy or lactation, surgical medical conditions, recent weight loss, excess alcohol intake, serious medical conditions, currently enrolled in commercial weight loss programs | Intervention:; [underlined: Portion control (PC)]: Individualized point system for foods based on energy, fiber, total fat in defined serving sizes based on current weight and target weight loss of 0.5–1kg/wk. Kept track of point values of foods consumed; [underlined: Energy density (LED)]: Followed a diet plan focused on low ED (not required to follow specified amount of food or tracking). Food intake monitored periodic assessment of hunger and satiety.; [underlined: Glycemic index (LGI)]: Dietary ad libitum plan based on foods from low glycemic index pyramid (not prescribed specific portions or tracking). Food intake monitored periodic assessment of hunger and satiety.; Duration: 12 weeks; Compliance: NR; Outcomes and assessment methods:; Baseline, 12 weeks; Weight, height, and waist circumference were measured by study personnel. Body composition was determined by validated air displacement plethysmography | Change in percent body fat; [underlined: PC]: −2.91 (2.59), p<0.001; [underlined: LED]: −3.87 (3.34), p<0.001; [underlined: LGI]: −2.65 (2.97), p<0.001; Between group: p=0.167; Fat Mass, kg; [underlined: PC]: −4.00 (3.2), p<0.001; [underlined: LED]: −4.98 (3.89), p<0.001; [underlined: LGI]: −3.64 (3.32), p<0.001; Between group: p=0.2.19; Fat free mass, kg; [underlined: PC]: 0.43 (1.15), p>0.05; [underlined: LED]: 0.78 (4.64), p>0.05; [underlined: LGI]: −0.51 (6.75), p>0.05; Between group: p=0.374; Waist circumference, cm; [underlined: PC]: −2.87 (3.18), p<0.001; [underlined: LED]: −4.06 (3.65), p<0.001; [underlined: LGI]: −3.31 (3.03), p<0.001; Between group: p=0.281; Change in BMI, kg/m^2^; Mean (SD); [underlined: PC]: −1.32 (1.03), p<0.001; [underlined: LED]: −1.36 (1.34), p<0.001; [underlined: LGI]: −1.11 (1.04), p<0.001; Between groups: p=0.539; Change in body mass, kg; Mean (SD); [underlined: PC]: −3.73 (2.84), p<0.001; [underlined: LED]: −4.14 (3.64), p<0.001; [underlined: LGI]: −3.39 (2.76), p<0.001; Between groups: p=0.509 | Model adjustments:; - None; Limitations:; - Methods for randomization and concealment NR; Power calculation not clear; Did not describe adherence or account for it in analyses; No preregistered data analysis plan; Funding:; NR
Poelman, 2015^6^; RCT-Parallel, PortionControl@Home, Netherlands; Baseline N=278, Analytic N=278 (Attrition: 0%); Study objective: To determine effectiveness of the “PortionControl@HOME” intervention on body mass index and portion control behavior; Participant characteristics at baseline: Adults with overweight/obesity who have the biggest food influence at home (responsible for groceries and making dinner); - [underlined: Age]: Mean (SD): 45.65 (9.20) y; - [underlined: Female]: 85%; - [underlined: Race and/or ethnicity]: Dutch nationality: 97% Other: 3% (Surinam, French, German); - [underlined: Socioeconomic position]: High education level: 43%; - [underlined: Anthropometry]:; BMI: 32.4 (4.8) kg/m^2^;; BMI >30: 65%; - [underlined: Physical activity]: NR; - [underlined: Smoking]: NR; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Those who reported having or having had co-morbidities including overweight and obesity, diabetes mellitus, cardiovascular disease, cancer, clinical depression; on a diet, visited a dietitian, or reported to be or have been in an intensive weight loss treatment within the past 6 months; pregnant or planning to become pregnant; BMI <25kg/m^2^; age <18 or >60 y; not residing in or within a distance of 15km of one of the participating six municipalities; were not the nutritional gatekeeper at home | Intervention:; [underlined: Portion Control @ Home Group]: Received the PortionControl@Home intervention with 4 elements:; 1. PortionSize@warenessTool: Interactive online tool to increase awareness of portion size and energy intake, recommended serving sizes, factors contributing to large portions; 2. Portion Control Strategies: Video, book, and assignments including action planning, coping planning, and self-monitoring; 3. Portion Control cooking class: Techniques to lower energy density through 3-biweekly cooking classes; 4. Portion Control Home-Screener: Screener assessed the home food environment. Based on screening, participants were provided with feedback on changes to improve home that stimulated portion size selection and intake; Intervention group received 3 online portion control boosters via email repeating intervention content between 3 and 12-month follow ups.; [underlined: Control Group]: Wait-list control group; Duration: 3 months; Compliance: 3 months: 61% intervention, 80% control; 6 months: 76% intervention, 85% control; 12 months: 64% intervention, 73% control; Models were run with and without n=3 for being outliers (>3 SD above or below mean % weight change); Outcomes and assessment methods:; Baseline, 3, 6, 12-month follow-ups; Weight and height were measured by study personnel at baseline (T0, T2 for weight, T0 for height); self-report weight at T1 and T3 | BMI (kg/m^2^), β (95% CI); [underlined: 3 mo]: −0.42 (−0.91, 0.07); [underlined: 3 mo no outliers]: −0.45 (−0.88, −0.44); p<0.05; [underlined: 6 mo]: −0.13 (−0.63, 0.37); [underlined: 6 mo no outliers]: −0.23 (0.66, 0.19); [underlined: 12 mo]: −0.03 (−0.53, 0.47); [underlined: 12 mo no outliers]: −0.19 (−0.62, 0.24) | Model adjustments:; - TEI: No; - Other: Dieting behavior in the period prior to measurement, time, time*intervention; Limitations:; - Differences in attrition (higher dropout rates in the intervention group); Outcome measured by self-report at some timepoints; No preregistered data analysis plan; Funding:; Dutch Institute for Research in Health Care
Eykelenboom, 2020^7^; PCS, PortionControl@Home, Netherlands; Analytic N=175; Study objective: To identify weight loss patterns and their determinants in adults with overweight and obesity; Participant characteristics at baseline: Adults with overweight/obesity who have the biggest food influence at home (responsible for groceries and making dinner); - [underlined: Age]: Mean (SD); 46.5 (9.4) y; - [underlined: Female]: 86%; - [underlined: Race and/or ethnicity]: NR; - [underlined: Socioeconomic position]: High education level: 46%; - [underlined: Anthropometry]: BMI: 31.8 (4.8) kg/m^2^; - [underlined: Physical activity]: NR; - [underlined: Smoking]: NR; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Those who reported having or having had co-morbidities including overweight and obesity, diabetes mellitus, cardiovascular disease, cancer, clinical depression; on a diet, visited a dietitian, or reported to be or have been in an intensive weight loss treatment with the past 6 months; pregnant or planning to become pregnant; BMI <25kg/m^2^; age <18 or >60 y; not residing in or within a distance of 15km of one of the participating six municipalities; were not the nutritional gatekeeper at home | Exposure:; [underlined: Portion Control @ Home Group]: Received the PortionControl@Home intervention with 4 elements:; 1. PortionSize@warenessTool: Interactive online tool to increase awareness of portion size and energy intake, recommended serving sizes, factors contributing to large portions; 2. Portion Control Strategies: Video, book, and assignments including action planning, coping planning, and self-monitoring; 3. Portion Control cooking class: Techniques to lower energy density through 3-biweekly cooking classes; 4. Portion Control Home-Screener: Screener assessed the home food environment. Based on screening, participants were provided with feedback on changes to improve home that stimulated portion size selection and intake; Intervention group received 3 online portion control boosters via email repeating intervention content between 3 and 12-month follow ups; [underlined: Control Group]: Wait-list control group; Three weight loss patterns were identified:; [underlined: Low success]: Low weight loss achievement, [underlined: Moderate success]: Successful weight loss in Phase 1 followed by partial regain in Phase 2 [underlined: High success]: Weight loss in Phase 1 followed by continued weight loss in Phase 2; Assessment methods and timing:; 32 item questionnaire; Baseline, 3 month; Outcomes and assessment methods:; Baseline, 3 months, 12 months; Weight and height were measured by study personnel at T0. Weight was self-reported at T1 and T3. | Change in portion control behavior and weight Loss patterns, OR (95% CI); [underlined: Moderate success], ref; [underlined: Low success]: 0.28 (0.10, 0.78); p=0.01; [underlined: High success]: 0.45 (0.13, 1.53); p=0.20 | Model adjustments:; - TEI: No; - Key confounders: None; - Other: Intervention treatment condition; Limitations:; - Did not account for key confounders: Sex, age, race and/or ethnicity, socioeconomic position, anthropometry at baseline, physical activity, smoking; - Portion control behavior was not a well-defined exposure and was only measured at baseline and 3 months; Outcome was self-reported and not well defined ("weight loss success"); Did not adjust for TEI; No preregistered data analysis plan; Funding:; Dutch Institute for Research in Health Care
Rock, 2016^8^; RCT-Parallel, U.S.; Baseline N=184, Analytic N=183 (Attrition: 1%); Study objective: To test whether providing portion-controlled pre-packaged lunch and dinner entrees within a behavioral weight loss intervention promotes greater weight loss at 12 weeks compared to self-selected foods in adults with overweight/obesity; Participant characteristics at baseline: Adults, 25–65 y; BMI 27–40 kg/m^2^; - [underlined: Age]: Mean (SD): 46.6 (0.8) y; - [underlined: Female]: 58%; - [underlined: Race and/or ethnicity]: Non-Hispanic White: 52.5%; African American: 10.3%; Asian American: 7.1%; Mixed/other: 8.2%; Hispanic: 21.9%; - [underlined: Socioeconomic position]: Education: 15.9 (0.2) y; - [underlined: Anthropometry]: BMI: 33.2 (3.5) kg/m^2^; - [underlined: Physical activity]: NR; - [underlined: Smoking]: NR; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Pregnant or breastfeeding; unwilling to participate in any of the study arms over a 3-month period; eating disorders, food allergies, or intolerances; history of bariatric surgery; inability to participate in physical activity; a history or presence of a comorbid disease for which diet modification and increased physical activity may be contraindicated; currently involved in another diet intervention study or organized weight loss program; and a history of significant psychiatric disorder or other condition would interfere with participation | Intervention:; [underlined: Portion-controlled entrees]: Portion-controlled pre-packaged lunch and dinner entrees 7 d/week + behavioral weight loss intervention (diet and physical activity); [underlined: Higher protein portion-controlled entrees]: Portion-controlled pre-packaged higher protein (>25% of energy) lunch and dinner entrees 7 d/week + behavioral weight loss intervention (diet and physical activity); [underlined: Self-selected diet]: Self-selected diet + behavioral weight loss intervention (diet and physical activity); Duration: 12 weeks; Compliance: 100% adherence at 2 weeks, 80% adherence at 12 weeks; Outcomes and assessment methods:; Baseline, 12 weeks; Weight and waist circumference were measured by study personnel, body composition was measured using DEXA | Waist, cm (baseline, 12 wks); [underlined: Portion-controlled entrees]: 111.9 (1.2), 102.1 (1.2); [underlined: Higher protein portion-controlled entrees]: 109.6 (1.2), 100.8 (1.2); [underlined: Self-selected diet]: 112.0 (1.5), 104.6 (1.5); P<0.001 within groups, P=NS between groups; Fat mass, kg (baseline, 12 wks); [underlined: Portion-controlled entrees]: 39.9 (1.0), 33.6 (1.1); [underlined: Higher protein portion-controlled entrees]: 38.3 (0.9), 32.9 (1.1); [underlined: Self-selected diet]: 40.4 (1.3), 36.2 (1.2); P<0.001 within groups, P<0.05 for portion-control vs selected groups; Fat mass, % lost; [underlined: Portion-controlled entrees]: 15.8 (1.0); [underlined: Higher protein portion-controlled entrees]: 14.4 (1.2); [underlined: Self-selected diet]: 10.7 (1.2) P=NS between groups; BMI, kg/m^2^ (baseline, 12 wks); [underlined: Portion-controlled entrees]: 33.3 (0.4), 30.6 (0.4); [underlined: Higher protein portion-controlled entrees]: 32.8 (0.4), 30.2 (0.4); [underlined: Self-selected diet]: 33.5 (0.6), 31.6 (0.6); P<0.001 within groups, P=NS between groups; Weight, kg (baseline, 12 wks); [underlined: Portion-controlled entrees]: 96.0 (1.7), 87.7 (1.6)*; [underlined: Higher protein portion-controlled entrees]: 95.8 (2.1), 87.9 (1.9); [underlined: Self-selected diet]: 95.9 (2.3), 90.1 (2.2); P<0.001 within groups, P=NS between groups; % Weight change (2 wks, 4 wks, 12 wks); [underlined: Portion-controlled entrees]: −3.0 (0.2), −4.4 (0.2), −8.6 (0.5); [underlined: Higher protein portion-controlled entrees]: −2.7 (0.2), −4.3 (0.3), −7.8 (0.6); [underlined: Self-selected diet]: −2.4 (0.3), −3.5 (0.3), −6.0 (0.7); P<0.001 within groups, P<0.01 for portion-control vs selected groups | Model adjustments:; - TEI: No; Limitations:; - Methods for randomization concealment NR; Minimal information provided about adherence to the study protocol; No preregistered data analysis plan; Funding:; Nestle USA, UCSD School of Medicine
Rolls, 2017^9^; RCT-Parallel, U.S.; Baseline N=186, Analytic N=151 (Attrition: 19%); Study objective: To test whether the efficacy of a behavioral weight-loss program was improved by incorporating either of the two portion-control strategies instead of standard advice about eating less; Participant characteristics at baseline: Adults, women, 20–65y, BMI 28–45 kg/m^2^; - [underlined: Age]: Mean (SD): 50 (11) y; - [underlined: Female]: 100%; - [underlined: Race and/or ethnicity]: White: 98%; African American: 1%; More than 1 race: 1%; Hispanic: 1% (Not Hispanic: 99%); - [underlined: Socioeconomic position]: Some college: 30%, College degree: 31%, Graduate degree: 25%; - [underlined: Anthropometry]: BMI: ~34 kg/m^2^; - [underlined: Physical activity]: Steps per day: ~6500; - [underlined: Smoking]: NR; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Blood pressure >160/100 mm Hg, reported a weight change >4.5 kg in the past 3 months, had a medical condition that precluded participation or that limited physical activity, were following a special diet or weight-loss program, were pregnant or lactating, scored >19 on the Eating Attitudes Test or >25 on the Beck Depression Inventory, did not complete all activities during 2-week run-in. | Intervention:; [underlined: Standard advice]: Follow dietary guidelines that emphasized eating less while making healthy choices from all food groups.; [underlined: Portion selection]: Instructed to choose food portions based on energy density (ED) in order to eat satisfying portions of low-ED foods and to control portions of higher-ED foods. Were provided with portion-selection tools (food scale, household measures, placemat for appropriate portions, card for portion estimations using common objects).; [underlined: Pre-portioned foods]: Instructed to structure their meals and to learn appropriate food portions by using pre-portioned foods, such as individual servings of main dishes, side dishes, snacks, yogurt, and whole fruits. Participants were instructed to eat pre-portioned main dishes daily for lunch and dinner during months 1–3 of the trial and were encouraged to continue this practice subsequently. Given pre-paid vouchers for single-serving main dishes (14 vouchers per week in month 1).; Duration: 12 months; Compliance: 35 were lost to follow-up at 1 year; Outcomes and assessment methods: Weight, waist circumference:; Baseline, 1-month, 3-month, 6-month, 12-month.; Weight and waist circumference were measured by study personnel. | Waist circumference, cm, all groups:; [underlined: Baseline]: 108.4 (9.8); [underlined: 3 mo]: 105.0 (10.7); [underlined: 6 mo]: 102.4 (10.7); [underlined: 12 mo]: 102.5 (11.2); p of time: p<0.0001; Weight loss at 3mo:; [underlined: Standard advice]: 3.7 (0.4) kg; [underlined: Portion selection]: 3.8 (0.4) kg; [underlined: Pre-portioned foods]: 5.1 (0.4) kg; P<0.05 for pre-portioned vs. standard, portion selection; Weight loss at 6mo:; [underlined: All groups]: 5.2 (0.4) kg; P<0.05 vs baseline; Weight loss at 12mo:; [underlined: All groups]: 4.5 (0.5) kg; P<0.05 vs baseline | Model adjustments:; - TEI: No; Limitations:; - None; Funding:; NIH; Food vouchers from ConAgra Foods, Inc, Nestlé USA.
Roe, 2020^10^; RCT-Parallel, Portion Control Strategies Trial, U.S. Baseline N=186, Analytic N=143 (Attrition: 23%); Study objective: To characterize the most commonly reported problem foods and the behavioral strategies used to manage them, and examined which strategies were related to weight loss; Participant characteristics at baseline: Women, 20–65 y with BMI 28–45 kg/m^2^; - [underlined: Age]: Mean (SD): 50 (10.6) y; - [underlined: Female]: 100%; - [underlined: Race and/or ethnicity]: Non-Hispanic White: 97%; - [underlined: Socioeconomic position]: College degree: 55%; - [underlined: Anthropometry]:; BMI: 34 (4.2) kg/m^2^;; Overweight: 19%;; Obesity: 81%; - [underlined: Physical activity]: NR; - [underlined: Smoking]: NR; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Blood pressure >160/100 mm Hg, reported a weight change >4.5 kg in the past 3 months, had a medical condition that precluded participation or that limited physical activity, were following a special diet or weight-loss program, were pregnant or lactating, scored >19 on the Eating Attitudes Test or >25 on the Beck Depression Inventory, did not complete all activities during 2-week run-in. | Intervention:; [underlined: Standard advice]: Follow dietary guidelines focusing on eating less while incorporating healthy options from all food groups.; [underlined: Portion Selection]: Trained to use energy density (ED) to select food portions and provided food scales and other portion-control tools.; [underlined: Pre-portioned foods]: Instructed to structure meals around pre-portioned foods and provided vouchers for single-serving main dishes, at a decreasing rate over duration of trial; Duration: 12 months; Compliance: 43 did not complete The Problem Foods Questionnaire at 12 months; Outcomes and assessment methods: Weight: 23 sessions over the 12-month trial.; Weight was measured by study personnel. | Weight change, kg; [underlined: All intervention groups]: More frequent use of limiting portions: greater rate of weight loss, p<0.0001; Pre-portioned group vs. standard and portion selection: Those who infrequently used limiting portions had greater initial weight loss, but regained weight at greater rate, p<0.0001 | Model adjustments:; - TEI: No; - Other: Number of intervention sessions attended, time; Limitations:; - None; Funding:; NIH
Tapsell, 2014^11^; RCT-Parallel, Australia; Baseline N=120, Analytic N=93 (Attrition: 23%); Study objective: To assess the effect of higher vegetable consumption on weight loss; Participant characteristics at baseline: Adults, 18–65 y, BMI 25–35 kg/m^2^; - [underlined: Age]: Mean (SD): 49 (9.3) y; - [underlined: Female]: 75%; - [underlined: Race and/or ethnicity]: NR; - [underlined: Socioeconomic position]: NR; - [underlined: Anthropometry]: BMI: ~30 (2.7) kg/m^2^; - [underlined: Physical activity]: Baecke: ~7.6 (1.4); - [underlined: Smoking]: NR; - [underlined: TEI]: ~2,100 (560) kcal/d; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Major illnesses, diabetes mellitus, thyroid abnormalities, heavy alcohol consumption, recent acute or chronic disease, changing medications affect weight, weight loss >5 kg in last 3 months, fluctuating exercise patterns, strenuous exercise >1 h per day, pregnancy or lactation, dietary limitations, and dislike of vegetables | Intervention:; [underlined: Vegetable intake 100%]: Personalized diet prescription based on core food groups from the Australian Guide to Healthy Eating, consume at least 5 servings/d of vegetables (0.5 cup cooked, 1 cup raw).; [underlined: Vegetable intake 200%]: Personalized diet prescription based on core food groups from the Australian Guide to Healthy Eating, consume at least 5 servings/d of vegetables (1 cup cooked, 2 cup raw).; Duration: 12 months; Compliance: Compared with the controls, the comparator group reported consuming a significantly greater proportion of energy intake from vegetables; Outcomes and assessment methods: 0, 1, 2, 3, 6, 9, and 12 months; Weight was measured by study personnel; body fat percentage measured with bio-electrical impedance | Baseline, 12 mo; Body fat (%); [underlined: Vegetables, 100%]: 40.5 (37.50–43.00), 38.10 (32.35–41.25); [underlined: Vegetables, 200%]: 38.55 (33.90–42.82), 36.75 (28.77–40.45); P, time <0.0001; P, group = 0.280; Waist (cm); [underlined: Vegetables, 100%]: 98.48 (9.39), 92.80 (8.13); [underlined: Vegetables, 200%]: 97.44 (9.32), 90.77 (9.40); P, time <0.0001; P, group = 0.489; Hip (cm); [underlined: Vegetables, 100%]: 108.56 (7.24), 103.74 (6.79); [underlined: Vegetables, 200%]: 109.34 (7.64), 103.30 (8.47); P, time <0.0001; P, group = 0.621; BMI (kg/m^2^); [underlined: Vegetables, 100%]: 29.84 (2.57), 27.79 (2.35); [underlined: Vegetables, 200%]: 30.11 (2.89), 27.51 (2.57); P, time <0.0001; P, group = 0.657; Weight (kg); [underlined: Vegetables, 100%]: 84.89 (9.86), 79.02 (9.32); [underlined: Vegetables, 200%]: 84.60 (13.05), 77.02 (10.74); P, time <0.001; P, group = 0.949 | Model adjustments:; - None; Limitations:; - None; Funding:; Horticulture Australia Limited, Australian Government
Webber, 2013^12^; RCT-Parallel, U.S.; Baseline N=50, Analytic N=47 (Attrition: 6%); Study objective: To evaluate the short-term impact of portion-controlled food provision in combination with an internet behavioral weight loss program on weight, blood cholesterol, and blood glucose levels; Participant characteristics at baseline: Adults, 25–65 y, with BMI >30 and <45 with home computer access; - [underlined: Age]: Mean (SD): 46 (10.7) y; - [underlined: Female]: 86%; - [underlined: Race and/or ethnicity]: Caucasian: 76%; - [underlined: Socioeconomic position]: College degree or higher: 62%; - [underlined: Anthropometry]:; BMI: 35.1 (3.8) kg/m^2^;; Waist circumference: 109.9 (12.4) cm; - [underlined: Physical activity]: NR; - [underlined: Smoking]: NR; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Those <25 or >65 yrs; with a medical diagnosis of orthopedic or joint problems that may prohibit exercise; reported heart problems, chest pain, faintness, or dizzy spells; hospitalization for a psychiatric disorder within the last year; a history of anorexia or bulimia nervosa; blood pressure >160/100; a medical diagnosis of cancer (except skin cancer) or HIV; pregnant, nursing, or planning pregnancy; <9 months postpartum; weight loss of 10 pounds in the last 6 months; >1 medication for hypertension control; taking glipizide, glyburide, insulin, or any agent to control diabetes mellitus that could cause hypoglycemia; taking warfarin; taking a diuretic with or without potassium supplementation; and food allergies. | Intervention:; [underlined: Internet + Portion Controlled Diet (Internet + PCD)]: Internet-based behavioral weight loss intervention + portion-controlled diet foods provided via Nutrisystem; [underlined: Internet-Alone]: Internet-based behavioral weight loss intervention; Duration: 12 weeks; Compliance: 3 did not complete final measurements from intervention group. Attrition was not significantly different between groups (p=0.23); Outcomes and assessment methods:; Baseline, 12 weeks; Weight and waist circumference were measured by study personnel | Baseline, 12 weeks; Change in waist circumference, cm; Mean (SD); [underlined: Internet + PCD]: −6.9 (5.3), p<0.001; [underlined: Internet-alone]: −5.8 (5.3), p<0.001; Between-group difference: p=0.48; Weight change, kg; Mean (SD); [underlined: Internet + PCD]: −5.7 (5.6), p<0.001; [underlined: Internet-alone]: −4.1 (4.4), p<0.001; Between group difference: p=0.26 | Model adjustments:; - None; Limitations:; - Methods for randomization and concealment NR; Sample size for power calculation not clear; No preregistered data analysis plan; Funding:; The Obesity Society and Nutrisystem, Inc.

a Abbreviations: β: Beta coefficient; BMI: Body Mass Index; CI: Confidence Interval; cm: Centimeters; d/week: days per week; DEXA: Dual X-ray Absorptiometry; DASH: Dietary Approaches to Stop Hypertension; ED: Energy density; h: hour; HED: High energy density; HIV: Human Immunodeficiency Virus; Inc.: Incorporated; Km: kilometer; kcal/d: Kilocalories per day; Kcal: Kilocalories; Kg: Kilogram; kg/m^2^:kilograms per meter squared; lb: Pound; LED: Low energy density; LGI: Low glycemic index; MetS: Metabolic syndrome; Mo: Month; Mins/d: Minutes per day; mm HG: millimeters of mercury; Mon-Fri: Monday – Friday; NIH: National Institutes of Health; NS: Not significant; NR: Not Reported; OR: Odds ratio; PC: Portion control; PCD: Portion control diet; %: percent (age); PCS: Prospective Cohort Study; ref: reference; RCT: Randomized Controlled Trial; Servings/d: Servings per day; SD: Standard Deviation; TO, T1, T2: Time; TEI: Total Energy Intake; UCSD: University of California San Diego; U.S./USA: United States/United States of America; Wk: Week; y/yrs: Year (s)

Table 11 Risk of bias for randomized controlled trials examining portion size and body composition or risk of obesity in adults and older adults^b^

Article | Randomization | Deviations from intended interventions (effect of assignment) or (per-protocol) | Missing outcome data | Outcome measurement | Selection of the reported result | Overall risk of bias
Cook, 2017 ^2^ | LOW | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS
Faucher, 2010 ^3^ | SOME CONCERNS | LOW | HIGH | HIGH | LOW | HIGH
French, 2014 ^4^ | HIGH | SOME CONCERNS | LOW | LOW | SOME CONCERNS | HIGH
Melanson, 2012 ^5^ | SOME CONCERNS | HIGH | LOW | LOW | SOME CONCERNS | HIGH
Poelman, 2015 ^6^ | LOW | SOME CONCERNS | LOW | HIGH | LOW | HIGH
Rock, 2016 ^8^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Rolls, 2017 ^9^ | LOW | LOW | LOW | LOW | LOW | LOW
Roe, 2020 ^10^ | LOW | LOW | HIGH | LOW | LOW | SOME CONCERNS
Tapsell, 2014 ^11^ | LOW | LOW | LOW | LOW | LOW | LOW
Webber, 2013 ^12^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS

b Possible ratings of low, some concerns, or high determined using the "Cochrane Risk-of-bias 2.0" (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2019 version)” ( Sterne JAC, Savović J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ 2019; 366: 14898. )

Table 12 Risk of bias for observational studies examining portion size and body composition and risk of obesity in adults and older adults^c^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Eykelenboom, 2020 ^7^ | VERY HIGH | SOME CONCERNS | LOW | LOW | HIGH | HIGH | SOME CONCERNS | VERY HIGH

c Possible ratings of low, some concerns, high, very high, no information, or not applicable were determined using the "Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)" tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602. ) *Low risk of bias except for concerns about uncontrolled confounding.

Table 13 Evidence examining the relationship between portion size and gestational weight gain in individuals during pregnancy^a^

Study and Population Characteristics | Intervention, Comparator, and Outcomes | Results | Confounding and Study Limitations
Blumfield, 2016^13^; PCS, Women and Their Children’s Health (WATCH) Study, Australia; Analytic N=134; Study objective: To examine the relationships between dietary portion size, gestational weight gain, and nutrient intakes during pregnancy; Participant characteristics at baseline:; Pregnant adults; - [underlined: Age]: Mean (SD): 29 (5.6) y; - [underlined: Female]: 100%; - [underlined: Race and/or ethnicity]: NR; - [underlined: Socioeconomic position]: Education level > Australian year 12 high school certificate: 46%; Socioeconomic status, IRSAD decile <5: 31 %; Married or in de facto relationship: 87%; - [underlined: Anthropometry]:; Pre-pregnancy weight status; 4.5% underweight,; 53% normal weight,; 24% overweight,; 19% obese; - [underlined: Physical activity]: NR; - [underlined: Smoking]: Smoked in pregnancy: 11%; - Parity: Nulliparous: 43%; - [underlined: Diabetes]: 4.5%; - [underlined: Hypertensive Disorders]: Hypertension: 6.7%; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: No exclusion criteria used. | Exposure:; [underlined: Portion Size Factor]:; Average (median serving size); Small (less than median serving size); Large (more than median serving size); Assessment methods and timing:; 74-item Food Frequency Questionnaire 18–24 weeks, 36–40 weeks; Outcomes and assessment methods: 18–24 weeks, 36–40 weeks; Self-report pre-pregnancy weight; Weight during pregnancy was measured by study personnel; Gestational weight gain was calculated using self-reported pre-pregnancy weight and research personnel measured weight at 36 weeks gestation | Gestational weight gain β (95% CI),; [underlined: Low SES]:−0.04 (−2.55, 2.04), P=0.82; [underlined: High SES]: 0.20 (0.07, 2.61), P=0.04; [underlined: Normal pre-pregnancy BMI]: −0.04 (− 1.56, 1.10) P=0.73; [underlined: Overweight/obese pre-pregnancy BMI]: 0.28 (0.12, 3.75) P=0.04; Adherence to IOM guidelines for weight gain during pregnancy:; [underlined: Low SES]: −0.12 (−0.39, 0.19), P=0.45; [underlined: High SES]: 0.21 (0.02, 0.33) P=0.04; [underlined: Normal pre-pregnancy BMI]: 0.00(− 0.20, 0.20) P=0.99; [underlined: Overweight/obese pre-pregnancy BMI]: 0.22 (−0.002, 0.43), P=0.05; Consuming larger average portion sizes was associated with higher gestational weight gain and greater adherence to IOM weight gain recommendations in those with high SES (not low SES), and in those with pre-pregnancy overweight or obesity (not normal weight). | Model adjustments:; - TEI: No; - Key confounders: Sex, Age, Socioeconomic Position, Smoking; Limitations:; - Did not account for key confounders: race and/or ethnicity, anthropometry at baseline, physical activity; - Measurement and development of exposure categories was not well described; Exposure measurement occurred between weeks 18–24, and did not include intakes during the first 18 weeks of pregnancy; Did not account for the types of foods that were consumed in relation to median portion sizes; Only reported results stratified by SES and pregnancy weight status; No pre-registered data analysis plan; Funding:; University of Newcastle, the Newcastle Permanent Charitable Foundation and the John Hunter Hospital Charitable Trust

a Abbreviations: β: beta coefficient; BMI: body mass index; CI: confidence interval; IRSAD: Index of Relative Socio-economic Advantage and Disadvantage; IOM: Institute of Medicine; NR: not reported; PCS: prospective cohort study; SES: socioeconomic status; SD: standard deviation; TEI: total energy intake; y: year

Table 14 Risk of bias for observational studies examining portion size and gestational weight gain in individuals during pregnancy^a^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Blumfield, 2016^13^ | SOME CONCERNS | VERY HIGH | SOME CONCERNS | HIGH | HIGH | LOW | HIGH | VERY HIGH

a Possible ratings of low, some concerns, high, very high, no information, or not applicable were determined using the "Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)" tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602. ) *Low risk of bias except for concerns about uncontrolled confounding.