# Results

## Literature search and screening results

Articles included in this systematic review were identified from literature searches conducted to identify all potentially relevant articles for this systematic review and a systematic review assessing the relationship between portion size and pre-portioned foods and energy intake.^†^ The intervention/exposures of interest for this review, portion size and pre-portioned foods, were considered together. The literature search (Appendix 2) yielded 6,050 search results after the removal of duplicates (see Figure 2). Dual-screening resulted in the exclusion of 4,775 titles, 883 abstracts, and 304 full-texts articles. Reasons for full-text exclusion are in Appendix 3. One additional article was identified from the manual search. The body of evidence included 13 articles:

- [underlined: Portion size in young children, children, and adolescents]: 1 article
- [underlined: Portion size in adults and older adults]: 11 articles
- [underlined: Portion size in individuals during pregnancy]: 1 article
- [underlined: Portion size in individuals during postpartum]: 0 articles

† Andres A, Fisher JO, Anderson CAM, Gardner CD, Giovannucci E, Hoelscher DM, Jernigan VBB, Odoms-Young A, Palacios C, Raynor HA, Stanford FC, Fultz, AK, Obbagy J, Butera G, Higgins M, Terry N. Portion Size and Energy Intake: A Systematic Review November 2024. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: 10.52570/NESR.DGAC2025.SR28

Figure 2 Literature search and screen flowchart

The literature search (Appendix 2) yielded 6,050 search results after the removal of duplicates (see Figure 2). Dual-screening resulted in the exclusion of 4,775 titles, 883 abstracts, and 304 full-texts articles. Reasons for full-text exclusion are in Appendix 3. One additional article was identified from the manual search. The body of evidence included 13 articles.

## Portion size in young children, children, and adolescents

### Description of the evidence

One article met inclusion criteria to examine the relationship between portion size and growth, body composition, and risk of obesity in young children, children, and adolescents.^1^ The article was a parallel randomized controlled trial (RCT) within a family-based intervention to test portion control tools. Evidence for portion size and growth, body composition, and risk of obesity in young children, children, and adolescents is summarized in Table 8.

#### Population

The trial was conducted in Canada with a sample size of N=73 and included majority females (57%).^1^ Children in the trial had a mean age of 11 years and a body mass index (BMI) z-score of 2.7 (0.4) at baseline. This trial did not report data on race and/or ethnicity or socioeconomic position of the participants.

#### Intervention/exposure and comparator

As part of the trial, children were randomized to a portion control group or control group. Children in the portion control group received counseling with portion control tools. The portion control tools included a portion control plate and breakfast bowl with the instruction to use the portion control plate at the largest meal of the day and the portion control bowl for cereal at breakfast. The control group received counseling with no portion control tools. Trial duration was 6 months.

#### Outcome

Change in weight, waist circumference, BMI, and BMI z-score were measured from baseline to 6 months.

### Synthesis of the evidence

There were no significant differences between the portion control tool group and control group for change in weight, waist circumference, BMI, and BMI z-score over the 6-month trial. Despite no significant difference between groups, the portion control tool group had lower waist circumference (cm) compared to the control group (-3.09 (19.2) cm vs. 1.94 (18.4) cm, P=0.26).

### Conclusion statement and grade

The 2025 Dietary Guidelines Advisory Committee developed a conclusion statement to answer the question, “What is the relationship between portion size and growth, body composition, and risk of obesity?” based on their review of the body evidence in young children, children, and adolescents (Table 4). The body of evidence includes 1 parallel randomized controlled trial with numerous risks of bias concerns across domains including the potential for deviations from intended intervention, differences in attrition that were not accounted for, and not being sufficiently powered (Table 9). While the literature search was comprehensive, a search of the gray literature was not conducted, and therefore there are some concerns that publication bias contributed to the lack of articles available for inclusion in this body of evidence.

Table 4 Conclusion statement and grade for portion size and growth, body composition, and risk of obesity in young children, children, and adolescents

Conclusion Statement | A conclusion statement cannot be drawn about the relationship between portion sizes consumed by young children, children, and adolescents and growth, body composition, and risk of obesity because there is not enough evidence available.
Grade | Grade Not Assignable
Body of Evidence | 1 article; RCT-parallel
Rationale | There is not enough evidence available to answer this question. The one study that was included had numerous risks of bias concerns.

## Portion size in adults and older adults

### Description of the evidence

Eleven articles met inclusion criteria to examine the relationship between portion size and body composition or risk of obesity in adults and older adults.^2–12^ Of the 11 articles, 10 were RCTs with parallel arms from 9 unique studies, and 1 article was a prospective cohort study (PCS) using secondary data from 1 the 10 trials. All trials were part of weight loss interventions. Evidence for portion size and body composition or risk of obesity in adults and older adults is summarized in Table 10.

#### Population

Sample size of study groups ranged from N=19 to N=278. Most of the trials were conducted in the U.S.^2–5,8–10,1^,^2^ with 2 conducted in The Netherlands^6,7^ and 1 in Australia.^11^ Mean age of participants was 46 years with a range between 18 to 65. Participants were predominately female with mean baseline BMI reported as approximately 32 kg/m^2^ with all studies including adults with overweight or obesity. Race and/or ethnicity of study participants was described in 9 of 11 articles. Two articles were conducted in The Netherlands in participants who were of 97% Dutch nationality.^6,7^ One study in the U.S. included 95% of participants that identified Mexico as their country of origin.^3^ The remainder of studies were conducted in the U.S. and reported race and ethnicity as follows, Non-Hispanic White: 52.5%, African American: 10.3%, Mixed/other: 8.2%, Hispanic: 21.9%;^8^ White: 69%;^4^ White: 98%, African American: 1%, More than 1 race: 1%, Hispanic: 1% (not Hispanic: 100%);^9^ Non-Hispanic White: 97%;^10^ White: 71%, Black/African American: ~20%, Multiracial: 4%, Other: 5%;^2^ Caucasian: 76%. Two articles did not describe race or ethnicity.^5,11^

Most articles provided some information about socioeconomic position of study participants, describing education, income, or marital status. In articles that reported information on education, participants had high levels of education including at least some college.^4,6–10,12^ Two studies reported information on income and marital status with 1 article in 100% females reporting ~21% worked outside the home and ~68% were married^3^ while in the other article, ~37% reported income >$80,000 and ~59% were married or living with a partner.^4^ Three articles did not report on socioeconomic position of study participants.^2,5,11^

Baseline physical activity and total energy intake were less often reported. Three articles provided information on baseline physical activity including ~27.5 minutes per day of moderate to vigorous activity,^4^ ~6,500 steps per day,^9^ and ~7.6 on the Baecke questionnaire.^11^ For baseline total energy intake, 1 article reported baseline total energy intake to be ~2,012 kcal/day,^4^ another reported ~2,014 kcal/day,^5^ and the last article, ~2,100 kcal/day.^11^

#### Intervention/exposure and comparator

Of the 9 unique trials, all were part of weight loss interventions and ranged in duration from 3 to 12 months. Six trials tested pre-portioned foods as the intervention/exposure^2,4,8–10,1^,^2^ while 5 educated participants on portion control strategies as a behavioral component to the intervention.^3,5–7,11^ Pre-portioned foods were either commercially prepared^2,8–10,1^,^2^ or researcher prepared4 and they all varied in terms of when participants were asked to consume the pre-portioned foods (e.g., lunch Mondays through Fridays, dinner, lunch and dinner).

One study tested regular and higher protein portion-controlled entrees for lunch and dinner compared to a self-selected diet with all groups receiving behavioral weight loss counseling.^8^ Another tested portion-controlled foods compared to a self-selected DASH diet advice group.^2^ Two articles from the same study^9,10^ tested a portion-controlled tools group and portion-controlled meals group compared to a standard Dietary Guideline advice group. The second study examined how participants in these groups managed problem foods associated with overconsumption using the strategy of limiting portion size.^9^ Another study tested pre-portioned foods in addition to an internet-based behavioral weight loss intervention compared to the internet-based behavioral intervention alone.^12^ Lastly, there was a study that tested different calorie amounts of boxed lunches compared to a control group.^4^

The remaining articles incorporated portion-controlled strategies into the intervention group of behavioral weight loss trials.^3,6,7^ Two studies tested a PortionControl@Home intervention using a portion control awareness online tool, education on portion control strategies using behavioral weight loss techniques (coping, self-monitoring, action planning), portion control cooking classes, and a portion control home screener to assess the home food environment with suggestive changes. The comparison was a wait-list control group.^6,7^ The second study in this set was a secondary analysis of the PortionControl@Home intervention where change in portion control behavior over the 3-month intervention was analyzed. Another study provided 4 classes on portion control as a dietary intervention compared to a control group that received 1 lesson on portion control and exercise.^3^ One study compared portion control to energy density and glycemic index groups^5^ and another focused solely on increasing the portion size of vegetables.^11^

#### Outcome

Outcomes included weight (weight loss, weight change), body composition measures (fat mass, fat-free mass, body fat percentage, body circumference), and risk of obesity measures (BMI). Weight and/or waist and body circumference were most often measured by study personnel at study baseline and final.^2,4,5,8–10,12^ One article specified weight measurements at baseline but did not report how final measurements were obtained.^3^ Two studies measured weight at baseline with self-report weight at final.^6,7^ Several articles measured body composition using validated techniques including Dual X-ray Absorptiometry (DEXA) for fat mass and fat-free mass,^2,8^ air displacement plethysmography,^5^ or bio-electrical impedance for body fat percentage.^11^ Outcomes were analyzed both within group (overall outcome changes) and between group (intervention, control).

### Synthesis of the evidence

For articles testing pre-portioned meals, only one found significant differences in body composition and weight loss between intervention and control groups as well as within group changes.^2^ However, while the intervention group showed greater reductions in all body composition measures, both groups lost body fat and body circumference beginning at week 4 with a continued decreased trend to week 16. One study reported no change in weight from baseline to 6 months for both the 400 and 800 calorie boxed lunch groups while weight change among participants in the 1600 calorie box lunch group increased significantly from baseline to 6 months.^4^ Despite the statistically significant increase in weight change in the 1600 calorie group, the mean weight change was 1.1(0.44) kg and was not different compared to the control group consuming their typical lunch (1.1 (0.42) kg). One article found that including portion control diet foods with an internet behavioral weight loss program resulted in greater weight loss (5.7 (5.6) kg) compared to the internet alone group (4.1 (4.4)kg), although this was not statistically significant.^12^ All other articles found significant within-group decreases in outcomes but no between group differences specifically related to portion-controlled pre-packaged meals.^8–10^

For articles related to behavioral weight loss interventions with a portion-controlled strategy group, there were only significant within-group changes, and no between-group changes associated with use of portion-controlled strategies.^3,5–7,11^ Despite the lack of statistical significance, results for one study showed the portion control group lost greater weight at 20 weeks compared to control (~6.5 pounds vs. 2.8 pounds).^3^ Another article found greater decreases in body composition measures for the low energy density group compared to portion control and low glycemic index groups.^5^ A weight loss of approximately 8 pounds was similar across the 3 groups. Studies had numerous risks of bias concerns across domains (Table 11 and Table 12). For RCTs, consistent concerns included a lack of detail on methods for randomization and concealment, no power analysis, and no pre-registered data analysis plans. Studies with higher risk of bias provided minimal information about adherence to study protocols, concerns with randomization due to baseline differences, unclear reporting of outcomes, lack of detail on missing data on exposure and outcomes, intervention groups receiving different dietary advice, and a lack of specificity on outcome measurements. For the PCS, risks of bias concerns were associated with not accounting for all key confounders, a lack of well-defined portion control behavior, measurement timing, self-reported outcome, and no pre-registered data analysis plan or protocol.

### Conclusion statement and grade

The 2025 Dietary Guidelines Advisory Committee developed a conclusion statement to answer the question, “What is the relationship between portion size and body composition or risk of obesity?” based on their review of the body evidence in adults and older adults (Table 5). The body of evidence includes 10 parallel-RCTs from 9 unique trials and 1 PCS using secondary data from 1 of the parallel-RCTs. While the studies all tested the use of portion size strategies, the studies varied widely in terms of how portion size was operationalized or implemented, what portion size strategies were compared to, how adherence was measured, duration of interventions, and what outcomes were measured. Given that most of the studies reported null findings, publication bias, though possibly present, was likely not a major concern within this body of evidence. Due to the inconsistency in the studies included in this body of evidence, a conclusion statement could not be developed.

Table 5 Conclusion statement and grade for portion size and body composition or risk of obesity in adults and older adults

Conclusion Statement | A conclusion statement cannot be drawn about the relationship between portion sizes consumed by adults and older adults and body composition or risk of obesity because of inconsistency in the interventions, comparators, and outcomes in the body of evidence.
Grade | Grade Not Assignable
Body of Evidence | 11 articles; 10 RCT-Parallel; 1 PCS from secondary analysis of 1 of the RCTs
Rationale | The body of evidence was inconsistent in the interventions, comparators, and outcomes examined. All included articles were part of weight loss trials.; - Six trials tested pre-portioned foods as the intervention/exposure.; - Five trials educated participants on portion control behaviors as part of behavioral weight loss interventions.; - Trials varied in duration and in what meal or food group was targeted for portion control (lunch and dinner, lunch only, vegetables, energy dense foods).; - Nine trials measured weight loss/maintenance as the primary outcome with body composition and risk of obesity measured less often.

## Portion size in individuals during pregnancy

### Description of the evidence

One article met inclusion criteria to examine the relationship between portion size and gestational weight gain in individuals during pregnancy.^13^ The article was a PCS. Evidence for portion size and gestational weight gain in individuals during pregnancy is summarized in Table 13.

#### Population

The PCS was conducted in Australia with a sample size of N=134 females. Pregnant women in the study had a mean age of ~29 years with 53% having normal pre-pregnancy weight. Race and/or ethnicity was not reported, however several factors were reported for socioeconomic position. Approximately 46% of participants had education higher than Australian year 12 high school certificate, 31% were living in an area less than 5 deciles according to the Index of Relative Socio-economic Advantage and Disadvantage (IRSAD) and 87% were married or in a de facto relationship.

#### Intervention/exposure and Comparator

As part of a 74-item food frequency questionnaire (FFQ), portion size information was collected in relation to a median serving size shown in the FFQ for vegetables, potatoes, steak, and casserole. A portion size factor (average, small, large) was created. The average portion size factor referred to the median serving size, small referred to less than the median serving size, and large referred to more than the median serving size. The FFQ was administered between 18–24 weeks gestation and again between 36–40 weeks.

#### Outcome

Gestational weight gain was calculated using participant self-reported pre-pregnancy weight and research personnel measured weight at 36 weeks gestation. In addition to gestational weight gain, adherence to Institute of Medicine (IOM) guidelines for weight gain during pregnancy was also assessed.

### Synthesis of the evidence

A significant association was found for participants who reported consuming larger portion sizes relative to the median and higher gestational weight gain as well as greater adherence to IOM weight gain recommendations. This was found in those with high socioeconomic status (SES) compared to low SES (Gestational weight gain: High SES: β (95% CI) = 0.20 (0.07, 2.6), p = 0.041 vs. Low SES: β (95% CI): -0.04 (-2.55, 2.04), P = 0.82; Adherence to IOM guidelines: High SES: β (95% CI): 0.21 (0.02, 0.33), P = 0.04 vs. Low SES: β (95% CI): -0.12 (-0.39, 0.19); P = 0.45) and in those with pre-pregnancy overweight or obesity compared to normal pre-pregnancy weight (Gestational weight gain: Normal pre-pregnancy: β (95% CI): -0.04 (-1.56, 1.10), P = 0.73 vs. Overweight/obesity: β (95% CI): 0.28 (0.12, 3.75), P = 0.04; Adherence to IOM guidelines: Normal pre-pregnancy: β (95% CI): 0.00 (-0.20, 0.20), P = 0.45; Overweight/obesity: β (95% CI): 0.22 (-0.002, 0.43), P = 0.05)). This study had numerous risks of bias concerns across domains including not accounting for all key confounders, lack of description on measurement and development of exposure categories, did not account for all types of food consumed in relation to the median portion size, only reported results stratified by SES and pregnancy weight status, and did not have a pre-registered protocol or data analysis plan (Table 14).

### Conclusion statement and grade

The 2025 Dietary Guidelines Advisory Committee developed a conclusion statement to answer the question, “What is the relationship between portion size and gestational weight gain?” based on their review of the body evidence in individuals during pregnancy (Table 6). The body of evidence includes 1 PCS with numerous risks of bias concerns. Due to the lack of evidence identified, it is difficult to evaluate publication bias. While the literature search was comprehensive, a search of the gray literature was not conducted, and therefore there are some concerns that publication bias contributed to the lack of articles available for inclusion in this body of evidence. The evidence was insufficient to develop a conclusion statement.

Table 6 Conclusion statement and grade for portion size and gestational weight gain during pregnancy

Conclusion Statement | A conclusion statement cannot be drawn about the relationship between portion sizes consumed during pregnancy and gestational weight gain because there is not enough evidence available.
Grade | Grade Not Assignable
Body of Evidence | 1 article; PCS
Rationale | There is not enough evidence available to answer this question.

## Portion size in individuals during postpartum

### Conclusion statement and grade

The 2025 Dietary Guidelines Advisory Committee developed a conclusion statement to answer the question, “What is the relationship between portion size and postpartum weight change?” (Table 7). There were no articles in the body of evidence, so a conclusion statement could be not drawn. Due to the lack of evidence identified, it is difficult to evaluate publication bias. While the literature search was comprehensive, a search of the gray literature was not conducted, and therefore there are some concerns that publication bias contributed to the lack of articles available for inclusion in this body of evidence.

Table 7 Conclusion statement and grade for portion size and postpartum weight change

Conclusion Statement | A conclusion statement cannot be drawn about the relationship between portion sizes consumed during postpartum and postpartum weight change because there is no evidence available.
Grade | Grade Not Assignable
Body of Evidence | 0 articles
Rationale | There is not enough evidence available to answer this question.